# Appendix 2 Conclusion statements from the existing systematic review

Table A 2 Conclusion statements from the existing systematic review for the research question: What is the relationship between dairy milk and milk alternative consumption and growth, body composition, and risk of obesity?

Citation | Conclusion statement and grade
Mayer-Davis E, Leidy H, Mattes R, Naimi T, Novotny R, Schneeman B, Kingshipp BJ, Spill M, Cole NC, Bahnfleth CL, Butera G, Terry N, Obbagy J. Beverage Consumption and Growth, Size, Body Composition, and Risk of Overweight and Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0401 | Limited evidence suggests that milk intake is not associated with adiposity in children. (Grade: Limited); Limited evidence suggests that higher milk intake is associated with a greater increase in height compared to lower intake in children. (Grade: Limited); Limited evidence suggests that milk intake is not associated with adiposity in adults. (Grade: Limited); Insufficient evidence is available to draw a conclusion about the relationship between the type of milk (i.e., milk fat content, flavor) and adiposity in children. (Grade: Grade not assignable)