# References of the articles included in the systematic review

1 Santos LP, Ong KK, Santos IS, Matijasevich A, Barros AJD. Effects of dietary intake patterns from 1 to 4 years on BMI z-score and body shape at age of 6 years: a prospective birth cohort study from Brazil. Eur J Nutr. 2019;58(4):1723–1734.doi: 10.1007/s00394-018-1720-3.29774385
2 Gómez-Donoso C, Martínez-González M, Martínez JA, Sayón-Orea C, de la Fuente-Arrillaga C, Bes-Rastrollo M. Adherence to dietary guidelines for the Spanish population and risk of overweight/obesity in the SUN cohort. PLoS One. 2019;14(12):e0226565.doi: 10.1371/journal.pone.0226565.31891595
3 Jarman M, Mathe N, Ramazani F, Dietary Patterns Prior to Pregnancy and Associations with Pregnancy Complications. Nutrients. 2018;10(7).doi: 10.3390/nu10070914.
4 Grummon AH, Cabana MD, Hecht AA, Effects of a multipronged beverage intervention on young children's beverage intake and weight: a cluster-randomized pilot study. Public Health Nutr. 2019;22(15):2856–2867.doi: 10.1017/S1368980019001629.31303190