# Results

## Literature search and screening results

Articles included in this systematic review were identified from literature searches conducted to identify all potentially relevant articles for 5 systematic reviews assessing the relationship between beverage consumption (beverage patterns, dairy and milk alternatives^†^; 100% juice^‡^; low- and no-calorie sweetened beverages^§^; and sugar sweetened beverages^**^) and growth, body composition, and risk of obesity. The literature searches yielded 36,223 search results after the removal of duplicates (Figure 2). Dual-screening resulted in the exclusion of 33,121 titles, 2,552 abstracts, and 463 full-texts articles. Reasons for full-text exclusion are in Appendix 3. No beverage pattern articles were identified from the manual search. The body of evidence examining beverage patterns, specifically, included four articles.

† Raynor HA, Deierlein AL, Gardner CD, . Dairy Milk and Milk Alternatives and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR03

‡ Deierlein AL, Raynor, HA, Andres A, . 100% Juice and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review Available at: 10.52570/NESR.DGAC2025.SR05

§ Deierlein AL, Raynor HA, Anderson CAM, . Low- and No-Calorie Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR04

** Deierlein AL, Raynor HA, Andres A, . Sugar-Sweetened Beverages and Growth, Body Composition, and Risk of Obesity: A Systematic Review with Meta-Analysis. November 2024. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2025.SR23

- Children and adolescents: 2 articles
- Adults and older adults: 1 article
- Individuals during pregnancy and postpartum: 1 article

Figure 2 Literature search and screen flowchart

The literature searches in PubMed, Embase, Cochrane, and CINAHL, retrieved 36,223 records after removing duplicates. 167 were included from existing reviews. 38 were found with manual search methods. 33,121 titles, 2,552 abstracts, and 463 full-texts were excluded. 292 articles were included across the five systematic reviews examining beverage consumption and growth, body composition, and risk of obesity.

Description of the evidence

The body of evidence examining the relationship between beverage pattern consumption and growth, body composition, and risk of obesity included four articles. Three articles were from prospective cohort studies (PCS)^1–3^, and the fourth was a randomized controlled trial (RCT)^4^. The following sections summarize the body of evidence used to answer this systematic review question, and the overall conclusion statement and grade is detailed in Table 5.

### Population

#### Children and adolescents

Evidence for consumption of beverage patterns in children and growth, body composition, and risk of obesity is summarized in Table 6, with risk of bias assessments detailed in Table 7 and Table 8. The two studies in children focused on younger children, with the 161 participants in the RCT averaging an age of four years^4^, and the PCS enrolling 3,374 participants age two to six.^1^ Both studies enrolled roughly half female, half male participants. The RCT was conducted in the U.S. and enrolled a 90% Hispanic population of predominantly lower socioeconomic position, while the PCS enrolled an exclusively Brazilian population with parent-reported skin color of White (71%), Brown (16%), and Black (13%) who were also of lower socioeconomic position.

There was no eligible evidence in the adolescent population.

#### Adults and older adults

Evidence for consumption of beverage patterns in adults and body composition, and risk of obesity is summarized in Table 9, with the risk of bias assessment detailed in Table 10. The PCS in adults was conducted in Spain and enrolled 11,554 highly educated adults with normal weight at baseline.^2^

There was no eligible evidence in the older adult population.

#### Individuals during pregnancy and postpartum

Evidence for consumption of beverage patterns in pregnancy and gestational weight gain is summarized in Table 11, with the risk of bias assessment detailed in Table 12. The PCS in individuals during pregnancy enrolled 1,545 predominantly white, well-educated participants during the first or second trimester of pregnancy.^3^

There was no eligible evidence in individuals during postpartum.

### Intervention/exposure

Beverage patterns were defined as the quantities, proportions, variety, or combination of different beverages in diets, and the frequency with which they are habitually consumed.

The beverage patterns examined across studies varied substantially.

- The RCT utilized a 12-week childcare center-based intervention that promoted “healthier beverages” such as water and unsweetened low- or non-fat milk while recommending limits on less healthy beverages such as SSB and sweetened and/or whole-fat milk.^4^
- The PCS in children used principal component analysis to identify dietary patterns including two beverage-specific patterns, one characterized by positive loading for juice and negative loading for soft drinks, and a second pattern characterized by positive loading for cow’s milk and chocolate powder.^1^
- The PCS in adults assessed the Sociedad Española de Nutricion Comunitaria (SENC) hydration pyramid (HP) score, which is intended to align with the Spanish dietary guidelines and reflects proportional intake of water, low/non-caloric beverages, caloric beverages with nutrients, and calorically sweetened beverages without nutrients.^2^
- The PCS during pregnancy used principal component analysis to identify a “tea and coffee” beverage pattern characterized by more frequent intake of coffee, tea, milk, cream, and added sugar.^3^

### Comparator

The RCT compared the intervention group to a non-intervention control group.^4^ All three PCS compared different levels of adherence to the beverage pattern or score of interest.^1–3^

### Outcome

The studies in children examined age- and sex-adjusted BMI percentile at follow up. The RCT also examined overweight/obesity incidence at follow up^4^, and the PCS also examined trunk and gynoid fat mass percentage z-scores at follow up.^1^

The PCS in adults assessed incidence of overweight/obesity at follow up.^2^

The PCS during pregnancy examined adequacy of total gestational weight gain (GWG) as defined by the IOM guidelines.^3^

## Synthesis of the evidence

The relationship between beverage pattern intake in children and the outcomes of interest was non-significant in both studies. However, no conclusion could be drawn due to the substantial variation between beverage patterns in the two studies. The RCT intervened on beverage intake with the aim of increasing consumption of “healthier beverages”^4^, while the PCS assessed habitual beverage intake in free-living participants.^1^ The beverage patterns, themselves, varied in how they were defined and assessed (e.g., predefined vs. data-driven) and which beverage types were represented in each pattern. Neither beverage pattern identified in the PCS was comparable to the beverage pattern in the RCT.

There was only one study, a PCS, on beverage pattern consumption in adults and body composition and risk of obesity. Results from that study showed no associations between the SENC hydration pyramid score and incident overweight/obesity over a median of 10 years follow up.

There was only one study, a PCS, on beverage pattern consumption during pregnancy and gestational weight gain. Results from that study showed no significant association between consumption of a “tea and coffee” beverage pattern and adequacy of total gestational weight gain.

The small number of eligible studies combined with the substantial differences between them and a generally high risk of bias prevented conclusions from being drawn on the relationship between beverage pattern consumption across all life stages and growth, body composition, or risk of obesity. Publication bias may also be a limitation, and the small body of evidence makes it difficult to assess.

## Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement^*^ to answer the question: What is the relationship between beverage patterns consumed and growth, body composition, and risk of obesity?” based on their review of the body of evidence (Table 5).

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

Table 5 Conclusion statement and grade for beverage patterns and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between beverage pattern consumption and growth, body composition, and risk of obesity because there is not enough evidence available.
Grade | Grade Not Assignable
Body of Evidence | 4 articles: 1 RCT (in children) and 3 prospective cohort studies (1 each in children, adults, and individuals during pregnancy)
Rationale | - The body of evidence varied in the beverage patterns and life stages examined, with several life stages having no evidence, or just one study included.; - Childhood was the only life stage with more than one included study. However, the two included studies in children differed substantially in how they defined beverage patterns (e.g., predefined vs. data-driven) and which beverage types were represented in each pattern.

## Research recommendations

The Committee identified the following research recommendations that describe the research, data, and methodological advances that are needed to strengthen the body of evidence on beverage pattern consumption and growth, body composition, and risk of obesity.

- Further develop methodology for adequately studying beverage patterns. Examining beverage patterns is difficult due to the substitution behaviors that can occur between different types of beverages (i.e., beverages that have calories and those that do not, the influence of different proportions of beverages relative to others), between beverages and food, and the relative contribution of beverages to total food and beverage intakes. Thus, investigations of beverage patterns should:
  ○ Separate caloric and noncaloric beverages.
  ○ Separate beverages that tend to replace foods and those that do not.
  ○ Examine how intake of one beverage affects intake of other beverages and foods.
  ○ Develop consistent ways of measuring beverage patterns, including accounting for total energy intake.
- Report data consistently across studies. All beverage types that comprise a pattern should be reported rather than characterizing patterns on the predominantly consumed beverage type.
- Increase amount and representation of research being conducted. All populations are underrepresented in the current body of evidence. Beverage consumption varies considerably across the lifespan, indicating a particular need for additional research in different age groups.

Table 6 Evidence examining the relationship between beverage pattern consumption in children and growth, body composition, and risk of obesity^a^

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcomes | Results | Confounding and Study Limitations
Grummon, 2019^4^; RCT-Cluster, U.S.; Baseline N=4 clusters, 161 participants; Analytic N=154 (Attrition: 4%); Power: No power analysis conducted (pilot study); Participant characteristics at baseline: Predominantly Hispanic/Latino children of lower SEP; - [underlined: Age]: Mean (SD) ~4y (0.52) (Range: 2–5y); - [underlined: Female]: 46%; - [underlined: Race/ethnicity]: Hispanic ethnicity in parents: Intervention: 98%; Control: 82%; - [underlined: SEP]: [underlined: Parental education], high school degree or less: Intervention: 66%; Control: 54%; - [underlined: Parental marriage status]: Married Intervention: 66%; Control: 65%; - [underlined: Annual household income ≤$30,000:] Intervention: 67%; Control: 67%; - [underlined: Anthropometry]: Baseline BMI, kg/m^2^ Intervention: Ovwt/Ob: 43%; Control: Ovwt/Ob: 39%; - [underlined: Physical activity]: NR; - [underlined: Diet quality]: NR; - [underlined: TEI]: NR; Study beverage intake at baseline:; Adjusted means (oz/day); - [underlined: All less-healthy beverages]: Intervention, 13.1; Control, 13.9; - [underlined: All healthier beverages]: Intervention, 13.8; Control, 8.3; Inclusion criteria: Licensed childcare, ≥10 children 2–5y enrolled, English or Spanish-speaking staff, primarily English or Spanish-speaking families, and participation in the Child and Adult Care Food Program (CACFP) | Intervention: The intervention promoted consumption of healthier beverages (i.e., water and unsweetened low- or non-fat milk) and recommended limiting consumption of less-healthy beverages (i.e., replacing juice with whole fruit and limiting SSBs, including sweetened and/or high-fat milk, to no more than one serving per week).; intervention was delivered via child care centers and consisted of environmental changes, policies and educational activities.; Other beverage interventions: N/A; Comparator: No intervention; Duration: 12wk; Compliance: Weekly, unannounced “spot check” observations of intervention classrooms to determine whether staff served water during meals/snacks, post-intervention to assess compliance on other aspects of intervention, tracking the number of parents who returned a completed behavioral contract; Outcomes and assessment methods:; - Measured at: Baseline, 12 wk; - Height and weight: valid measure by study staff; - BMI: calculated from height and weight measurements. BMI percentile calculated using CDC age- and sex-specific growth charts. Children were classified as having overweight/obesity if their BMI percentile was at or above 85th percentile for age and sex. | [underlined: Change in BMI Percentile], point estimate (95% CI), generalized linear regression Intervention: 0.7 (−1.3, 2.6); Control: −0.5 (−3.6, 2.5); Difference-in-differences: 1.2 (−2.5, 4.9) P=NS; [underlined: Change in likelihood of having overweight/obesity], point estimate (95% CI), predicted probabilities and marginal effects (i.e., percentage point change in likelihood of having overweight/obesity), generalized linear regression; Intervention: −3% (−10%, 3%); Control: 3% (−4%, 9%); Difference-in-differences: −6% (−15%, 3%) P=NS; [underlined: Change in Absolute BMI], kg/m^2^, point estimate (95% CI), generalized linear regression; Intervention: 0.2 (−0.1, 0.5); Control: 0.1 (−0.2, 0.4); Difference-in-differences: 0.03 (−0.2, 0.3) P=NS | Model adjustments:; - [underlined: TEI]: no; - [underlined: Key confounders]: N/A; - [underlined: Other]: Classroom fixed effects, clustering standard errors within children; Limitations:; - Methods for randomization and concealment NR;; - Concerns with deviations from intended intervention;; - No power calculation;; - No preregistered data analysis plan; Funding:; NIH; Carolina Population Center; Johns Hopkins Center for a Livable Future; Maternal and Child Health Bureau, HRSA, HHS
Santos, 2019^1^; PCS, Pelotas Birth Cohort Study (2004 cohort), Brazil; Analytic N=3,374; Participant characteristics at baseline:; Children from birth cohort; - [underlined: Age]: ~4y at first dietary assessment; - [underlined: Female]: 48%; - [underlined: Race/ethnicity]: All Brazilian: Children's skin color (maternal report): White: 71.4%, Brown: 15.5%, Black: 13.1%; - [underlined: SEP]: assessed by Brazilian National Wealth Index, which considers household assets and household head's education according to Brazilian Demographic Census data.; First quintile (poorest): 22.7%; Q2: 21.4%; Q3: 22.7%; Q4: 16.5%; Q5 (richest): 16.7%; - [underlined: Maternal years of formal education]: 0–4y: 15.1%; 5–8y: 42%; ≥9y: 43%; - [underlined: Anthropometry]: Birth weight ≥2500g: 91.4%; - [underlined: Physical activity]: NR; - [underlined: Diet quality]: NR; - [underlined: TEI]: NR; Study beverage intake at baseline: NR; Exclusion criteria: Missing data on BMI at 6y | Exposure: “Beverages” pattern characterized by positive loading for juice; negative loading for soft drinks; "Milks" pattern characterized by positive loading for cow's milk and chocolate powder; Other beverage exposures: N/A; Comparator: Different “milks” or “beverages” pattern component scores (categorical, by tertiles). T1=low score; T2=intermediate; T3=high score; Assessment methods and timing:; - PCA of dietary data derived from 24h dietary recall completed by child's mother. Data was collected on frequency of consuming each food/beverage item, but not amounts/portion sizes of each item.; - At 2y, 4y; Data also collected at 1y but was excluded from this extraction because of confounding with breast milk in exposure and because Brazil did not meet HDI criteria until the 2y data collection.; Outcomes and assessment methods:; - Weight: measured by BodPod; - Height: measured by stadiometer; - BMI calculated from height and weight; standardized by age and sex using WHO growth charts; - Waist circumference: measured by 3D Photonic Scanner; - Fat mass (trunk and gynoid): measured with DXA; - At 6y | [underlined: BMI z-score at 6y] by tertile of beverage pattern intake, β (95% CI), adjusted linear regression; [underlined: “Beverages” pattern at 2y]; T1: ref; T2: −0.03 (−0.16, 0.09); T3: −0.07 (−0.19, 0.06), P=0.306; [underlined: “Beverages” pattern at 4y]; T1: ref; T2: 0.05 (−0.07, 0.18); T3: −0.01 (−0.15, 0.12), P=0.846; [underlined: “Milks” pattern at 4y]; T1 (low intake): ref; T2: 0.03 (−0.10, 0.17); T3: 0.03 (−0.10, 0.16), P=0.65; [underlined: Trunk fat mass percentage z-score at 6y], β (95% CI), adjusted linear regression; [underlined: “Beverages” pattern at 2y]; T1: ref; T2: −0.02 (−0.11, 0.07); T3: 0.04 (−0.05, 0.13), P=0.372; [underlined: “Beverages” pattern at 4y]; T1: ref; T2: −0.01 (−0.10, 0.08); T3: 0.00 (−0.09, 0.09), P=0.954; [underlined: “Milks” pattern at 4y]; T1 (low intake): ref; T2: −0.02 (−0.11, 0.07); T3: 0.01 (−0.08, 0.10), P=0.763; [underlined: Gynoid fat mass percentage z-score at 6y] by tertile of beverage pattern intake, β (95% CI), adjusted linear regression; [underlined: “Beverages” pattern at 2y]; T1: ref; T2: 0.02 (−0.07, 0.11); T3: −0.01 (−0.10, 0.08), P=0.89; [underlined: “Beverages” pattern at 4y]; T1: ref; T2: 0.01 (−0.08, 0.10); T3: 0.04 (−0.05, 0.13), P=0.44; [underlined: “Milks” pattern at 4y]; T1 (low intake): ref; T2: −0.03 (−0.13, 0.06); T3: −0.06 (−0.16, 0.03), P=0.172 | Model adjustments:; - [underlined: TEI]: no; - [underlined: Key confounders]: sex, age, race and/or ethnicity, socioeconomic position, diet quality (adjusted for similar-labeled components at 1y and 2y data collection, respectively); - [underlined: Other]: Number of siblings, maternal age at birth and education, smoking during pregnancy, birth weight, exclusive breastfeeding duration, number of meals per day; Limitations:; - Did not account for key confounders: anthropometry at baseline, physical activity; - No preregistered data analysis plan; Funding:; Wellcome Trust, WHO, Brazilian National Research Council, Brazilian Ministry of Health, Science Without Borders

a Abbreviations: BMI: body mass index; g: gram; CDC: Centers for Disease Control and Prevention; DXA: Dual-energy X-ray Absorptiometry; HHS: Department of Health and Human Services; HRSA: Health Resources and Services Administration; N/A: Not applicable; NIH: National Institutes of Health; NR: Not reported; P: P-value; PCA: Principal component analysis; Ref: Reference group; SEP: socioeconomic position, TEI: total energy intake; U.S.: United States; WHO: World Health Organization; wk: week; y: year

Table 7 Risk of bias for randomized controlled trials examining beverage pattern consumption in children and growth, body composition, and risk of obesity^a^

Article | Identification of participants - Randomization | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Grummon, 2019^4^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Table 8 Risk of bias for observational studies examining beverage pattern consumption in children and growth, body composition, and risk of obesity^b^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Santos, 2019^1^ | SOME CONCERNS | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 9 Evidence examining the relationship between beverage pattern consumption in adults and body composition and risk of obesity^*^ * Abbreviations: BMI: body mass index; g: gram; CVD: Cardiovascular disease; DXA: Dual-energy X-ray Absorptiometry; FFQ: Food frequency questionnaire; METs: metabolic equivalent of task; N/A: Not applicable; NR: Not reported; P: P-value; PCA: Principal component analysis; Ref: Reference group; SEP: socioeconomic position, TEI: total energy intake; U.S.: United States; wk: week; y: year

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcomes | Results | Confounding and Study Limitations
Gómez-Donoso, 2019^2^; PCS, Seguimiento Universidad de Navarra (SUN) cohort, Spain; Analytic N=11,554; Participant characteristics at baseline: Highly educated Spanish adults who were normal weight at baseline; - [underlined: Age]: Mean (SD): 34.7 (10.8) y; - [underlined: Female]: 73%; - [underlined: Race/ethnicity]: NR; - [underlined: SEP]: Years of education at university, mean (SD): 5.0 (1.5); % unemployed: 6.2%; % married: 43%; % living alone: 7.1%; - [underlined: Anthropometry]: Mean BMI: 21.7 kg/m^2^; - [underlined: Physical activity]: Mean METs-h/wk: 23.4; - [underlined: Smoking]: Never smokers: 52.9%, Current smokers: 22.5%; - [underlined: Diet quality]: Svg/d: Mean (SD) Fruit: 2.9, Vegetables: 2.3 (1.3); - [underlined: TEI]: Mean: T1: 2,632; T2: 2,288; T3: 2,169; Study beverage intake at baseline: Servings/d, Mean; - [underlined: T1]: water: 5.8; low/non-caloric and non-nutritive: 1.1; caloric & nutritive: 3.1; calorically sweetened & non-nutritive: 0.4; water from foods: 7.4; - [underlined: T2]: water: 3.8; low/non-caloric and non-nutritive: 0.7; caloric & nutritive: 2.2; calorically sweetened & non-nutritive: 0.3; water from foods: 5.2; - [underlined: T3]: water: 3.9; low/non-caloric and non-nutritive: 1.4; caloric & nutritive: 1.3; calorically sweetened & non-nutritive: 0.3; water from foods: 5.2; Exclusion criteria: overweight or obesity at baseline (BMI ≥25), implausible TEI, pregnancy, chronic disease (diabetes, CVD, and/or cancer), weight change >10kg in previous 5y, lost to follow-up, missing data on variables of interest | Exposure: Sociedad Española de Nutricion Comunitaria (SENC) hydration pyramid (HP) score:; Recommendations were:; - 10 combined serv/d of water, low/non-caloric beverages, caloric and nutritive beverages, and water coming from foods (score range 0–10 with potential for 10 bonus points if intake hierarchy was consumption of water > low/non-caloric beverages > caloric beverages), and; - <1 serv/d of calorically sweetened beverages without nutrients (score range 0–10); Other beverage exposures: N/A; Comparator: Adherence to SENC HP (categorical), classified into tertiles: T1: HP score <11 (lowest adherence), T2: HP score 11–15, T3: HP score >16; Assessment methods and timing: Semi-quantitative, validated FFQ representing intake over previous year; At baseline for all participants and 10-year follow-up for subset (38%); Outcomes and assessment methods:; - Weight and height: self-reported (validated with measurements in sub-sample); - Incident overweight and obesity: defined as having a BMI <25 at baseline and ≥25 at follow-up; - Measured at baseline and every 2 years | [underlined: Incident overweight/obesity] according to tertiles of adherences to SENC Hydration Pyramid, Cox proportional hazard model, HR (95% CI); T1 (lowest adherence): ref; T2: 1.01 (0.90, 1.12); T3: 1.01 (0.90, 1.13) P=0.908; [underlined: Incident overweight/obesity] according to tertiles of adherences to SENC Hydration Pyramid in participants with repeat diet assessments (n=4,407; 38% of sample), Cox proportional hazard model, HR (95% CI); T1 (lowest adherence): ref; T2: 1.00 (0.90, 1.11); T3: 1.01 (0.90, 1.12); P=0.899 | Model adjustments:; - [underlined: TEI]: yes; - [underlined: Key confounders:] sex, age, race and/or ethnicity, socioeconomic position, anthropometry at baseline, physical activity, smoking; - [underlined: Other]: Hours of TV watching, snacking between meals, following a special diet at baseline, family history of obesity, hours of siesta sleep; Limitations:; - Did not account for key confounders: Diet quality; - Exposure data only measured at baseline for most participants;; - No preregistered data analysis plan;; - Lack of generalizability to full Spanish population; Funding:; Spanish Government-Instituto de Salud Carlos III, European Regional Development Fund, the Navarra Regional Government, University of Navarra

Table 10 Risk of bias for observational studies examining beverage pattern consumption in adults and growth, body composition, and risk of obesity^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Gómez-Donoso, 2019^2^ | SOME CONCERNS | HIGH | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | HIGH

a a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 11 Evidence examining the relationship between beverage pattern consumption in pregnancy and gestational weight gain^*^ * Abbreviations: BMI: body mass index; g: gram; CVD: Cardiovascular disease; FFQ: Food frequency questionnaire; GWG: Gestational weight gain; N/A: Not applicable; NR: Not reported; P: P-value; PCA: Principal component analysis; Ref: Reference group; SEP: socioeconomic position, TEI: total energy intake; U.S.: United States; wk: week; y: year

Study and Population Characteristics | Intervention or Exposure, Comparator, and Outcomes | Results | Confounding and Study Limitations
Jarman, 2018^3^; PCS, Alberta Pregnancy Outcomes and Nutrition (APrON) Study, Canada; Analytic N=1,545; Participant characteristics at baseline:; Individuals during pregnancy; - [underlined: Age]: Mean (SD): 31.4 (4.2)y; - [underlined: Female]: 100%; - [underlined: Race/ethnicity]: White: 84%, Not White: 16%; - [underlined: SEP]: Education: Below university level: 28%, University level: 72% Household yearly income: <$100K: 42%, ≥$100K: 58%;; Marital status: Married/cohabitating: 97%, Single/divorced/widowed: 3%; - [underlined: Anthropometry]: Pre-pregnancy BMI: Underweight: 3%, Normal weight: 65%, Overweight: 21%, Obesity: 11%; - [underlined: Physical activity]: NR; - [underlined: Smoking]: Smoked during pregnancy: 1%; - [underlined: TEI]: NR; Study beverage intake at baseline: NR; Inclusion criteria: Participants were eligible for study if they were >16y, <27wk gestation, and literate in English.; Exclusion criteria: those with energy intakes <600 or >3500 kcal/d; underweight based on pre-pregnancy BMI | Exposure: "Tea and coffee pattern" characterized by more frequent intakes of coffee (regular and decaf), tea (regular, decaf, herbal), reduced-fat milk (1%, 2%, powdered, skim, soy), full-fat milk, cream, and added sugar.; Other beverage exposures: N/A; Comparator: Consumption of a different "tea and coffee" pattern score (continuous); Assessment methods and timing:; PCA of dietary data derived from validated FFQ (representing 12mo prior to becoming pregnant); Outcomes and assessment methods:; - Total GWG calculated by subtracting pre-pregnancy weight (self-reported) from the highest weight in pregnancy (self-reported at 3mo postpartum visit) and compared with IOM guidelines; - Measured at 3mo postpartum | [underlined: Adequacy of Total GWG (in excess of IOM guidelines)], OR (95% CI), multivariate regression; Unadjusted: 1.2 (1.0, 1.4); Adjusted: 1.1 (0.98, 1.3), P=0.07 | Model adjustments:; - [underlined: TEI]: yes; - [underlined: Key confounders:] socioeconomic position, anthropometry at baseline; - [underlined: Other]: N/A; Limitations:; - Did not account for key confounders: age, race and/or ethnicity, physical activity, diet quality, smoking, parity, diabetes mellitus in the current pregnancy, hypertensive disorders in the current pregnancy; - Exposure data only measured at baseline; Weight was self-reported; No preregistered data analysis plan; Funding:; Alberta Innovates Health Solutions

Table 12 Risk of bias for observational studies examining beverage pattern consumption in pregnancy and gestational weight gain^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Jarman, 2018^3^ | HIGH | LOW | LOW | LOW | LOW | HIGH | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool ( Higgins JPT, Morgan RL, Rooney AA, . A tool to assess risk of bias in non-randomized follow-up studies of exposure effects (ROBINS-E). Environment International 2024 (published online Mar 24); doi: 10.1016/j.envint.2024.108602. ) *Low risk of bias except for concerns about uncontrolled confounding.