# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body Mass Index
CNPP: Center for Nutrition Policy and Promotion
FNS: Food and Nutrition Service
GWG: Gestational weight gain
HDI: Human development index
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NGAD: Nutrition Guidance and Analysis Division
PCS: Prospective cohort study
RCT: Randomized controlled trial
USDA: United States Department of Agriculture