# References of included articles in this systematic review

1 Abraham EC, Godwin J, Sherriff A, Armstrong J. Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year. Public Health Nutr. Sep 2012;15(9):1705–14. doi:10.1017/S1368980012002686 22626031
2 Agnihotri N, Overby NC, Bere E, Wills AK, Brantsaeter AL, Hillesund ER. Childhood adherence to a potentially healthy and sustainable Nordic diet and later overweight: The Norwegian Mother, Father and Child Cohort Study (MoBa). Matern Child Nutr. Apr 2021;17(2):e13101. doi:10.1111/mcn.13101 33103349
3 Amaro-Rivera K, Molina J, Pérez CM, Palacios C. Longitudinal Associations between Dietary Patterns and Weight Status in Puerto Rican Infants and Toddlers' Participants of the WIC Program. Article. Puerto Rico health sciences journal. 2019;38(2):75–80.31260549
4 Au LE, Arnold CD, Ritchie LD, Frongillo EA. The Infant Diet Quality Index Predicts Dietary and Adiposity Outcomes in US Children 2 to 4 years old. J Nutr. Mar 2023;153(3):741–748. doi:10.1016/j.tjnut.2023.01.037 36806452
5 Baird J, Poole J, Robinson S, Milk feeding and dietary patterns predict weight and fat gains in infancy. Paediatr Perinat Epidemiol. Nov 2008;22(6):575–86.19000296
6 Bell LK, Golley RK, Daniels L, Magarey AM. Dietary patterns of Australian children aged 14 and 24 months, and associations with socio-demographic factors and adiposity. Eur J Clin Nutr. Jun 2013;67(6):638–45. doi:10.1038/ejcn.2013.23 23443830
7 Golley RK, Smithers LG, Mittinty MN, Emmett P, Northstone K, Lynch JW. Diet quality of U.K. infants is associated with dietary, adiposity, cardiovascular, and cognitive outcomes measured at 7–8 years of age. J Nutr. Oct 2013;143(10):1611–7. doi:10.3945/jn.112.170605 23946339
8 Hohman EE, Paul IM, Birch LL, Savage JS. INSIGHT responsive parenting intervention is associated with healthier patterns of dietary exposures in infants. Obesity (Silver Spring). Jan 2017;25(1):185–191. doi:10.1002/oby.21705 28008749
9 Jin H, Shan T, Li S, Association of infant feeding patterns with body fat mass and obesity in the first 2 years of life: a longitudinal twin birth cohort study. Article in Press. International journal of food sciences and nutrition. 2021:1–11. doi:10.1080/09637486.2021.1968357
10 Nguyen AN, Jen V, Jaddoe VWV, Diet quality in early and mid-childhood in relation to trajectories of growth and body composition. Clin Nutr. Mar 2020;39(3):845–852.30967308
11 Okubo H, Crozier SR, Harvey NC, Diet quality across early childhood and adiposity at 6 years: the Southampton Women's Survey. Int J Obes (Lond). Oct 2015;39(10):1456–62.26121960
12 Olaya GA, Lawson M, Fewtrell MS. Efficacy and safety of new complementary feeding guidelines with an emphasis on red meat consumption: a randomized trial in Bogota, Colombia. Am J Clin Nutr. Oct 2013;98(4):983–93. doi:10.3945/ajcn.112.053595 23945724
13 Robinson SM, Marriott LD, Crozier SR, Variations in infant feeding practice are associated with body composition in childhood: a prospective cohort study. J Clin Endocrinol Metab. Aug 2009;94(8):2799–805. doi:10.1210/jc.2009-0030 19435826
14 Rose CM, Savage JS, Birch LL. Patterns of early dietary exposures have implications for maternal and child weight outcomes. Obesity (Silver Spring). Feb 2016;24(2):430–8. doi:10.1002/oby.21349 26717908
15 Santos LP, Ong KK, Santos IS, Matijasevich A, Barros AJD. Effects of dietary intake patterns from 1 to 4 years on BMI z-score and body shape at age of 6 years: a prospective birth cohort study from Brazil. Article. European Journal of Nutrition. 2019;58(4):1723–1734.29774385
16 Vadiveloo M, Tovar A, Østbye T, Benjamin-Neelon SE. Associations between timing and quality of solid food introduction with infant weight-for-length z-scores at 12 months: Findings from the Nurture cohort. Article. Appetite. 2019;141
17 Voortman T, Leermakers ET, Franco OH, A priori and a posteriori dietary patterns at the age of 1 year and body composition at the age of 6 years: the Generation R Study. Eur J Epidemiol. Aug 2016;31(8):775–83.27384175
18 Wen X, Kong KL, Eiden RD, Sharma NN, Xie C. Sociodemographic Differences and Infant Dietary Patterns. Pediatrics. 2014;134(5):e1387–e1398. doi:10.1542/peds.2014-1045 25311608
19 Aljahdali AA, Peterson KE, Cantoral A, Diet Quality Scores and Cardiometabolic Risk Factors in Mexican Children and Adolescents: A Longitudinal Analysis. Nutrients. Feb 20 2022;14(4)doi:10.3390/nu14040896
20 Ambrosini GL, Johns DJ, Northstone K, Emmett PM, Jebb SA. Free Sugars and Total Fat Are Important Characteristics of a Dietary Pattern Associated with Adiposity across Childhood and Adolescence. J Nutr. Mar 9 2016;
21 Arenaza L, Medrano M, Oses M, The Effect of a Family-Based Lifestyle Education Program on Dietary Habits, Hepatic Fat and Adiposity Markers in 8–12-Year-Old Children with Overweight/Obesity. Nutrients. May 16 2020;12(5)
22 Arruda Neta AC, Farias Junior JC, Lima Ferreira FE, Marchioni DM. Prospective association between dietary patterns and BMI Z-score in Brazilian adolescents. Public Health Nutr. Sep 2021;24(13):4230–4237. doi:10.1017/S1368980021000252 33472719
23 Asghari G, Yuzbashian E, Mirmiran P, Hooshmand F, Najafi R, Azizi F. Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern Is Associated with Reduced Incidence of Metabolic Syndrome in Children and Adolescents. J Pediatr. Jul 2016;174:178–184.e1. doi:10.1016/j.jpeds.2016.03.077 27156186
24 Asoudeh F, Fallah M, Aminianfar A, The effect of Mediterranean diet on inflammatory biomarkers and components of metabolic syndrome in adolescent girls. J Endocrinol Invest. Oct 2023;46(10):1995–2004. doi:10.1007/s40618-023-02027-1 36795242
25 Bawaked RA, Fernandez-Barres S, Navarrete-Munoz EM, Impact of lifestyle behaviors in early childhood on obesity and cardiometabolic risk in children: Results from the Spanish INMA birth cohort study. Pediatr Obes. Mar 2020;15(3):e12590. doi:10.1111/ijpo.12590 31793235
26 Bekelman TA, Ringham BM, Sauder KA, Adherence to index-based dietary patterns in childhood and BMI trajectory during the transition to adolescence: the EPOCH study. Int J Obes (Lond). Jul 24 2021;
27 Biazzi Leal D, Altenburg de Assis MA, Hinnig PF, Changes in Dietary Patterns from Childhood to Adolescence and Associated Body Adiposity Status. Nutrients. Oct 6 2017;9(10)doi:10.3390/nu9101098
28 Buckland G, Taylor CM, Emmett PM, Johnson L, Northstone K. Prospective association between a Mediterranean-style dietary score in childhood and cardiometabolic risk in young adults from the ALSPAC birth cohort. Eur J Nutr. Mar 2022;61(2):737–752. doi:10.1007/s00394-021-02652-7 34532761
29 Bull CJ, Northstone K. Childhood dietary patterns and cardiovascular risk factors in adolescence: results from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort. Public Health Nutr. Dec 2016;19(18):3369–3377.27339189
30 Chan She Ping-Delfos WL, Beilin LJ, Oddy WH, Burrows S, Mori TA. Use of the Dietary Guideline Index to assess cardiometabolic risk in adolescents. Br J Nutr. Jun 14 2015;113(11):1741–52.25873301
31 Chang K, Khandpur N, Neri D, Association Between Childhood Consumption of Ultraprocessed Food and Adiposity Trajectories in the Avon Longitudinal Study of Parents and Children Birth Cohort. JAMA Pediatr. Sep 1 2021;175(9):e211573. doi:10.1001/jamapediatrics.2021.1573 34125152
32 Choy CC, Wang D, Naseri T, Longitudinal Assessment of Childhood Dietary Patterns: Associations with Body Mass Index z-Score among Children in the Samoan Ola Tuputupua'e (Growing Up) Cohort. Child Obes. Oct 2020;16(7):534–543.32907355
33 Costa CDS, Assuncao MCF, Loret de Mola C, Role of ultra-processed food in fat mass index between 6 and 11 years of age: a cohort study. Int J Epidemiol. Mar 3 2021;50(1):256–265. doi:10.1093/ije/dyaa141 32888008
34 Costa CDS, Buffarini R, Flores TR, Neri D, Freitas Silveira M, Monteiro CA. Consumption of ultra-processed foods and growth outcomes in early childhood: 2015 Pelotas Birth Cohort. Br J Nutr. Sep 12 2022:1–8. doi:10.1017/S0007114522002926
35 Costa CS, Rauber F, Leffa PS, Sangalli CN, Campagnolo PDB, Vitolo MR. Ultra-processed food consumption and its effects on anthropometric and glucose profile: A longitudinal study during childhood. Nutr Metab Cardiovasc Dis. Feb 2019;29(2):177–184. doi:10.1016/j.numecd.2018.11.003 30660687
36 Costa JP, Magalhaes V, Araujo J, Ramos E. A lower energy intake contributes to a better cardiometabolic profile in adolescence: Data from the EPITeen cohort. Nutr Res. Mar 2023;111:14–23. doi:10.1016/j.nutres.2023.01.002 36791661
37 Cunha DB, da Costa THM, da Veiga GV, Pereira RA, Sichieri R. Ultra-processed food consumption and adiposity trajectories in a Brazilian cohort of adolescents: ELANA study. Nutr Diabetes. May 25 2018;8(1):28. doi:10.1038/s41387-018-0043-z 29795367
38 Diethelm K, Günther AL, Schulze MB, Standl M, Heinrich J, Buyken AE. Prospective relevance of dietary patterns at the beginning and during the course of primary school to the development of body composition. Br J Nutr. Apr 28 2014;111(8):1488–98. doi:10.1017/s0007114513004017 24382029
39 Durao C, Severo M, Oliveira A, Association between dietary patterns and adiposity from 4 to 7 years of age. Public Health Nutr. Aug 2017;20(11):1973–1982.28534458
40 Durao C, Severo M, Oliveira A, Lopes C. Sex-Heterogeneity on the Association between Dietary Patterns at 4 Years of Age with Adiposity and Cardiometabolic Risk Factors at 10 Years of Age. Article. Nutrients. Jan 26 2022;14(3)doi:10.3390/nu14030540
41 Farhadnejad H, Asghari G, Mirmiran P, Azizi F. Dietary approach to stop hypertension diet and cardiovascular risk factors among 10- to 18-year-old individuals. Pediatr Obes. Apr 2018;13(4):185–194. doi:10.1111/ijpo.12268 29363277
42 Fernandez-Alvira JM, Bammann K, Eiben G, Prospective associations between dietary patterns and body composition changes in European children: the IDEFICS study. Public Health Nutr. Dec 2017;20(18):3257–3265.28879834
43 Gasser CE, Mensah FK, Clifford SA, Kerr JA, Cassim R, Wake M. Bidirectional associations between diet and body composition measures from 2 to 15 years: Longitudinal Study of Australian Children. Article. British Journal of Nutrition. Jan 28 2019;121(2):212–220. doi:10.1017/S0007114518003173 30375296
44 Pereyra Gonzalez I, Farias-Antunez S, Buffarini R, Ultra-processed food consumption and the incidence of obesity in two cohorts of Latin-American young children: A longitudinal study. J Pediatr Nurs. Mar-Apr 2023;69:e120–e126. doi:10.1016/j.pedn.2022.12.018 36604255
45 Heerman WJ, Sneed NM, Sommer EC, Ultra-processed food consumption and BMI-Z among children at risk for obesity from low-income households. Pediatr Obes. Aug 2023;18(8):e13037. doi:10.1111/ijpo.13037 37070567
46 Hu T, Jacobs DR, Jr L, N. I C, G. J L, M. N N-S. Higher Diet Quality in Adolescence and Dietary Improvements Are Related to Less Weight Gain During the Transition From Adolescence to Adulthood. J Pediatr. Nov 2016;178:188–193.e3.27640354
47 Johnson L, Mander AP, Jones LR, Emmett PM, Jebb SA. Energy-dense, low-fiber, high-fat dietary pattern is associated with increased fatness in childhood. Am J Clin Nutr. Apr 2008;87(4):846–54. doi:10.1093/ajcn/87.4.846 18400706
48 Krijger JA, Nicolaou M, Nguyen AN, Voortman T, Hutten BA, Vrijkotte TG. Diet quality at age 5–6 and cardiovascular outcomes in preadolescents. Clin Nutr ESPEN. 2021;43 doi:0.1016/j.clnesp.2021.02.011
49 Lee SY, Kim J, Oh S, A 24-week intervention based on nutrition care process improves diet quality, body mass index, and motivation in children and adolescents with obesity. Nutr Res. 2020;84doi:10.1016/j.nutres.2020.09.005
50 Lioret S, McNaughton SA, Cameron AJ, Three-year change in diet quality and associated changes in BMI among schoolchildren living in socio-economically disadvantaged neighbourhoods. Br J Nutr. Jul 28 2014;112(2):260–8.24775601
51 Luque V, Closa-Monasterolo R, Grote V, Dietary Patterns Acquired in Early Life are Associated with Cardiometabolic Markers at School Age. Clin Nutr. Jul 2021;40(7):4606–4614.34229265
52 Marinho AR, Severo M, Vilela S, Is the association between dietary patterns and cognition mediated by children's adiposity? A longitudinal approach in Generation XXI birth cohort. Clin Nutr. 2022;41(1)doi:10.1016/j.clnu.2021.11.029
53 Marks J, Barnett LM, Allender S. Change of School in Early Adolescence and Adverse Obesity-Related Dietary Behavior: A Longitudinal Cohort Study, Victoria, Australia, 2013–2014. Prev Chronic Dis. Sep 10 2015;12:E145. doi:10.5888/pcd12.150042 26355826
54 Martin-Calvo N, Chavarro JE, Falbe J, Hu FB, Field AE. Adherence to the Mediterranean dietary pattern and BMI change among US adolescents. Int J Obes (Lond). Jul 2016;40(7):1103–8.27102053
55 McCourt HJ, Draffin CR, Woodside JV, Dietary patterns and cardiovascular risk factors in adolescents and young adults: the Northern Ireland Young Hearts Project. Br J Nutr. Nov 28 2014;112(10):1685–98. doi:10.1017/s0007114514002682 25234582
56 Notario-Barandiaran L, Valera-Gran D, Gonzalez-Palacios S, High adherence to a mediterranean diet at age 4 reduces overweight, obesity and abdominal obesity incidence in children at the age of 8. Int J Obes (Lond). Sep 2020;44(9):1906–1917.32152497
57 Oellingrath IM, Svendsen MV. BMI-specific associations between health-related behaviours and overweight - a longitudinal study among Norwegian adolescents. Public Health Nutr. Feb 2017;20(3):481–491. doi:10.1017/S1368980016002536 27652897
58 Pala V, Lissner L, Hebestreit A, Dietary patterns and longitudinal change in body mass in European children: A follow-up study on the IDEFICS multicenter cohort. Article. European Journal of Clinical Nutrition. 2013;67(10):1042–1049.23942180
59 Papamichael MM, Katsardis C, Lambert K, Efficacy of a Mediterranean diet supplemented with fatty fish in ameliorating inflammation in paediatric asthma: a randomised controlled trial. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Journal of human nutrition and dietetics. 2019;32(2):185–197.30378203
60 Pinto A, Severo M, Oliveira A. Use of a hybrid method to derive dietary patterns in 7 years olds with explanatory ability of body mass index at age 10. Eur J Clin Nutr. Mar 5 2021;
61 Rashid V, Streppel MT, Engberink MF, Weijs PJM, Nicolaou M, Verhoeff AP. Weight development between age 5 and 10 years and its associations with dietary patterns at age 5 in the ABCD cohort. BMC Public Health. Apr 1 2020;20(1):427.32238152
62 Saldanha-Gomes C, Heude B, Charles MA, Prospective associations between energy balance-related behaviors at 2 years of age and subsequent adiposity: the EDEN mother-child cohort. Int J Obes (Lond). Jan 2017;41(1):38–45.27528250
63 Saldanha-Gomes C, Hallimat Cissé A, Descarpentrie A, Prospective associations between dietary patterns, screen and outdoor play times at 2 years and age at adiposity rebound: The EDEN mother-child cohort. Article. Preventive Medicine Reports. 2022;25doi:10.1016/j.pmedr.2021.101666
64 Setayeshgar S, Maximova K, Ekwaru JP, Diet quality as measured by the Diet Quality Index-International is associated with prospective changes in body fat among Canadian children. Public Health Nutr. Feb 2017;20(3):456–463. doi:10.1017/s1368980016002500 27660199
65 Shinsugi C, Tani Y, Kurotani K, Takimoto H, Ochi M, Fujiwara T. Change in Growth and Diet Quality Among Preschool Children in Tokyo, Japan. Nutrients. May 1 2020;12(5)
66 Siddiqui NZ, Nguyen AN, Santos S, Voortman T. Diet quality and cardiometabolic health in childhood: the Generation R Study. Eur J Nutr. Mar 2022;61(2):729–736. doi:10.1007/s00394-021-02673-2 34528119
67 Sirkka O, Fleischmann M, Abrahamse-Berkeveld M, Dietary Patterns in Early Childhood and the Risk of Childhood Overweight: The GECKO Drenthe Birth Cohort. Article. Nutrients. Jun 15 2021;13(6)doi:10.3390/nu13062046
68 Smith AD, Emmett PM, Newby PK, Northstone K. Dietary patterns and changes in body composition in children between 9 and 11 years. Food Nutr Res. 2014;58
69 Sorensen LMN, Aamodt G, Brantsaeter AL, Meltzer HM, Papadopoulou E. Diet quality of Norwegian children at 3 and 7 years: changes, predictors and longitudinal association with weight. Int J Obes (Lond). Aug 30 2021;
70 Temple JL, Mansouri T, Andrade ALP, Ziegler AM. The Influence of Relative Reinforcing Value of Food, Sensitization, Energy Intake and Diet Quality on zBMI Change over Two Years in Adolescents: A Longitudinal Cohort Study. Article. Nutrients. 2023;15(9)doi:10.3390/nu15092179
71 Tognon G, Hebestreit A, Lanfer A, Mediterranean diet, overweight and body composition in children from eight European countries: cross-sectional and prospective results from the IDEFICS study. Nutr Metab Cardiovasc Dis. Feb 2014;24(2):205–13.23870847
72 Vallejo RM, Schulz CA, van de Locht K, Oluwagbemigun K, Alexy U, Nöthlings U. Associations Between Adherence to a Dietary Index Based on the EAT-Lancet Reference Diet with Nutritional, Anthropometric and Ecological Sustainability Parameters: Results From the German DONALD Cohort Study. J Nutr. 2022;doi:10.1093/jn/nxac094
73 Vedovato GM, Vilela S, Severo M, Rodrigues S, Lopes C, Oliveira A. Ultra-processed food consumption, appetitive traits and BMI in children: a prospective study. British Journal of Nutrition. 2021;125(12):1427–1436.32962770
74 Vilela S, Magalhaes V, Severo M, Oliveira A, Torres D, Lopes C. Effect of the food processing degree on cardiometabolic health outcomes: A prospective approach in childhood. Clin Nutr. Oct 2022;41(10):2235–2243. doi:10.1016/j.clnu.2022.07.034 36081298
75 Vinke PC, Luitjens M, Blijleven KA, Navis G, Kromhout D, Corpeleijn E. Nutrition beyond the first 1000 days: diet quality and 7-year change in BMI and overweight in 3-year old children from the Dutch GECKO Drenthe birth cohort. J Dev Orig Health Dis. Dec 11 2020:1–7.31907091
76 Wolters M, Joslowski G, Plachta-Danielzik S, Dietary Patterns in Primary School are of Prospective Relevance for the Development of Body Composition in Two German Pediatric Populations. Nutrients. Oct 5 2018;10(10)doi:10.3390/nu10101442
77 Agnoli C, Sieri S, Ricceri F, Adherence to a Mediterranean diet and long-term changes in weight and waist circumference in the EPIC-Italy cohort. Nutr Diabetes. Apr 25 2018;8(1):22.29695712
78 Aljadani HM, Patterson AJ, Sibbritt DW, Taylor RM, Collins CE. Improving diet quality over nine-years is associated with less weight gain in mid-age Australian women: A cohort study. Nutr Metab Cardiovasc Dis. Feb 10 2020;30(2):223–232.31767421
79 Aljadani HM, Patterson A, Sibbritt D, Taylor RM, Collins CE. Frequency and variety of usual intakes of healthy foods, fruit, and vegetables predicts lower 6-year weight gain in young women. Eur J Clin Nutr. Jun 2020;74(6):945–952.31758163
80 Allaire BT, Tjaden AH, Venditti EM, Diet quality, weight loss, and diabetes incidence in the Diabetes Prevention Program (DPP). BMC Nutr. Dec 15 2020;6(1):74.33317629
81 Alvarez-Perez J, Sanchez-Villegas A, Diaz-Benitez EM, Influence of a Mediterranean Dietary Pattern on Body Fat Distribution: Results of the PREDIMED-Canarias Intervention Randomized Trial. J Am Coll Nutr. Aug 2016;35(6):568–580.27314172
82 André P, Proctor G, Driollet B, The role of overweight in the association between the Mediterranean diet and the risk of type 2 diabetes mellitus: a mediation analysis among 21 585 UK biobank participants. Int J Epidemiol. Oct 1 2020;49(5):1582–1590. doi:10.1093/ije/dyaa103 32754745
83 Angulo E, Stern D, Castellanos-Gutierrez A, Changes in the Global Diet Quality Score, Weight, and Waist Circumference in Mexican Women. J Nutr. Oct 23 2021;151(12 Suppl 2):152S–161S. doi:10.1093/jn/nxab171 34689194
84 Arabshahi S, Ibiebele TI, Hughes MCB, Lahmann PH, Williams GM, van der Pols JC. Dietary patterns and weight change: 15-year longitudinal study in Australian adults. Eur J Nutr. Jun 2017;56(4):1455–1465.26919993
85 Arjmand G, Abbas-Zadeh M, Fardaei M, Eftekhari MH. The Effect of Short-term Mediterranean-DASH Intervention for Neurodegenerative Delay (MIND) Diet on Hunger Hormones, Anthropometric Parameters, and Brain Structures in Middle-aged Overweight and Obese Women: A Randomized Controlled Trial. Article. Iranian Journal of Medical Sciences. 2022;47(5):422–432. doi:10.30476/IJMS.2021.90829.2180 36117580
86 Baldwin JN, Forder PM, Haslam RL, Change in Diet Quality over 12 Years in the 1946–1951 Cohort of the Australian Longitudinal Study on Women's Health. Nutrients. Jan 4 2020;12(1)
87 Baratali L, Mean M, Marques-Vidal P. Impact of dietary and obesity genetic risk scores on weight gain. Am J Clin Nutr. Aug 2 2021;114(2):741–751.33831948
88 Beslay M, Srour B, Mejean C, Ultra-processed food intake in association with BMI change and risk of overweight and obesity: A prospective analysis of the French NutriNet-Sante cohort. PLoS Med. Aug 2020;17(8):e1003256. doi:10.1371/journal.pmed.1003256 32853224
89 Best N, Flannery O. Association between adherence to the Mediterranean Diet and the Eatwell Guide and changes in weight and waist circumference in post-menopausal women in the UK Women's Cohort Study. Post Reprod Health. 2023;doi:10.1177/20533691231156643
90 Bouzas C, Bibiloni MDM, Garcia S, Desired weight loss and its association with health, health behaviors and perceptions in an adult population with weight excess: One-year follow-up. Front Nutr. 2022;9doi:10.3389/fnut.2022.848055
91 Bouzas C, Bibiloni MDM, Garcia S, Dietary Quality Changes According to the Preceding Maximum Weight: A Longitudinal Analysis in the PREDIMED-Plus Randomized Trial. Nutrients. Oct 2 2020;12(10)
92 Brayner B, Kaur G, Keske MA, Perez-Cornago A, Piernas C, Livingstone KM. Dietary Patterns Characterized by Fat Type in Association with Obesity and Type 2 Diabetes: A Longitudinal Study of UK Biobank Participants. J Nutr. Nov 2 2021;151(11):3570–3578. doi:10.1093/jn/nxab275 34522964
93 Bruno E, Oliverio A, Paradiso AV, A Mediterranean Dietary Intervention in Female Carriers of BRCA Mutations: Results from an Italian Prospective Randomized Controlled Trial. Cancers (Basel). Dec 11 2020;12(12)doi:10.3390/cancers12123732
94 Calvo-Malvar M, Benitez-Estevez AJ, Leis R, Sanchez-Castro J, Gude F. Changes in Dietary Patterns through a Nutritional Intervention with a Traditional Atlantic Diet: The Galiat Randomized Controlled Trial. Article. Nutrients. Nov 25 2021;13(12)doi:10.3390/nu13124233
95 Calvo-Malvar M, Benitez-Estevez AJ, Sanchez-Castro J, Leis R, Gude F. Effects of a Community-Based Behavioral Intervention with a Traditional Atlantic Diet on Cardiometabolic Risk Markers: A Cluster Randomized Controlled Trial ("The GALIAT Study"). Nutrients. Apr 7 2021;13(4)
96 Canhada SL, Vigo Á, Luft VC, Ultra-Processed Food Consumption and Increased Risk of Metabolic Syndrome in Adults: The ELSA-Brasil. Diabetes Care. Feb 1 2023;46(2):369–376. doi:10.2337/dc22-1505 36516280
97 Canhada SL, Luft VC, Giatti L, Ultra-processed foods, incident overweight and obesity, and longitudinal changes in weight and waist circumference: the Brazilian Longitudinal Study of Adult Health (ELSA-Brasil). Public Health Nutr. Oct 17 2019:1–11.
98 Casas R, Ribó-Coll M, Ros E, Change to a healthy diet in people over 70 years old: the PREDIMED experience. Eur J Nutr. 2022;doi:10.1007/s00394-021-02741-7
99 Cespedes Feliciano EM, Tinker L, Manson JE, Change in Dietary Patterns and Change in Waist Circumference and DXA Trunk Fat Among Postmenopausal Women. Obesity (Silver Spring). Oct 2016;24(10):2176–84.27548405
100 Chaltiel D, Julia C, Adjibade M, Touvier M, Hercberg S, Kesse-Guyot E. Adherence to the 2017 French dietary guidelines and adult weight gain: A cohort study. PLoS Med. Dec 2019;16(12):e1003007.31887145
101 Chen Z, Schoufour JD, Rivadeneira F, Plant-based Diet and Adiposity over Time in a Middle-aged and Elderly Population: The Rotterdam Study. Article. Epidemiology. 2019;30(2):303–310.30507650
102 Choi Y, Larson N, Gallaher DD, A Shift Toward a Plant-Centered Diet From Young to Middle Adulthood and Subsequent Risk of Type 2 Diabetes and Weight Gain: The Coronary Artery Risk Development in Young Adults (CARDIA) Study. Diabetes Care. Nov 2020;43(11):2796–2803.32847828
103 Cordova R, Kliemann N, Huybrechts I, Consumption of ultra-processed foods associated with weight gain and obesity in adults: A multi-national cohort study. Clinical Nutrition. 2021;40(9):5079–5088.34455267
104 Crosby L, Rembert E, Levin S, Changes in Food and Nutrient Intake and Diet Quality on a Low-Fat Vegan Diet Are Associated with Changes in Body Weight, Body Composition, and Insulin Sensitivity in Overweight Adults: A Randomized Clinical Trial. Article in Press. Journal of the Academy of Nutrition and Dietetics. 2022;doi:10.1016/j.jand.2022.04.008
105 Cuenca-Garcia M, Artero EG, Sui X, Lee DC, Hebert JR, Blair SN. Dietary indices, cardiovascular risk factors and mortality in middle-aged adults: findings from the Aerobics Center Longitudinal Study. Ann Epidemiol. Apr 2014;24(4):297–303.e2.24529647
106 Davis CR, Bryan J, Hodgson JM, Woodman R, Murphy KJ. A Mediterranean Diet Reduces F2-Isoprostanes and Triglycerides among Older Australian Men and Women after 6 Months. J Nutr. Jul 2017;147(7):1348–1355.28566524
107 Ericson U, Brunkwall L, Alves Dias J, Food patterns in relation to weight change and incidence of type 2 diabetes, coronary events and stroke in the Malmo Diet and Cancer cohort. Article. Eur J Nutr. Aug 2019;58(5):1801–1814. doi:10.1007/s00394-018-1727-9 29855685
108 Estruch R, Martínez-González MA, Corella D, Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial. Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. The lancet Diabetes & endocrinology. 2019;7(5):e6 e17.31003626
109 Ford C, Chang S, Vitolins MZ, Evaluation of diet pattern and weight gain in postmenopausal women enrolled in the Women's Health Initiative Observational Study. Br J Nutr. Apr 2017;117(8):1189–1197.28509665
110 Fung TT, Li Y, Bromage S, Higher Global Diet Quality Score Is Associated with Less 4-Year Weight Gain in US Women. J Nutr. Oct 23 2021;151(12 Suppl 2):162S–167S. doi:10.1093/jn/nxab170 34689192
111 Fung TT, Pan A, Hou T, Long-term change in diet quality is associated with body weight change in men and women. Article. Journal of Nutrition. 2015;145(8):1850–1856. doi:10.3945/jn.114.208785 26084363
112 Funtikova AN, Benitez-Arciniega AA, Gomez SF, Fito M, Elosua R, Schroder H. Mediterranean diet impact on changes in abdominal fat and 10-year incidence of abdominal obesity in a Spanish population. Br J Nutr. Apr 28 2014;111(8):1481–7.24382017
113 Georgoulis M, Yiannakouris N, Kechribari I, Cardiometabolic Benefits of a Weight-Loss Mediterranean Diet/Lifestyle Intervention in Patients with Obstructive Sleep Apnea: The "MIMOSA" Randomized Clinical Trial. Nutrients. May 28 2020;12(6)doi:10.3390/nu12061570
114 Georgoulis M, Yiannakouris N, Kechribari I, Sustained improvements in the cardiometabolic profile of patients with obstructive sleep apnea after a weight-loss Mediterranean diet/lifestyle intervention: 12-month follow-up (6 months post-intervention) of the "MIMOSA" randomized clinical trial. Nutr Metab Cardiovasc Dis. May 2023;33(5):1019–1028. doi:10.1016/j.numecd.2023.02.010 36958969
115 Georgoulis M, Yiannakouris N, Kechribari I, The effectiveness of a weight-loss Mediterranean diet/lifestyle intervention in the management of obstructive sleep apnea: Results of the "MIMOSA" randomized clinical trial. Clin Nutr. Mar 2021;40(3):850–859. doi:10.1016/j.clnu.2020.08.037 32928580
116 Glenn AJ, Hernandez-Alonso P, Kendall CWC, Longitudinal changes in adherence to the portfolio and DASH dietary patterns and cardiometabolic risk factors in the PREDIMED-Plus study. Clin Nutr. May 2021;40(5):2825–2836. doi:10.1016/j.clnu.2021.03.016 33933749
117 Gomez-Donoso C, Martinez-Gonzalez MA, Gea A, Murphy KJ, Parletta N, Bes-Rastrollo M. A food-based score and incidence of overweight/obesity: The Dietary Obesity-Prevention Score (DOS). Clin Nutr. Dec 2019;38(6):2607–2615.30522848
118 Gómez-Donoso C, Martínez-González MÁ, Martínez JA, A provegetarian food pattern emphasizing preference for healthy plant-derived foods reduces the risk of overweight/obesity in the SUN cohort. Article. Nutrients. 2019;11(7)
119 Gomez-Donoso C, Martinez-Gonzalez MA, Martinez JA, Sayon-Orea C, e la Fuente-Arrillaga C, Bes-Rastrollo M. Adherence to dietary guidelines for the Spanish population and risk of overweight/obesity in the SUN cohort. PLoS One. 2019;14(12):e0226565.31891595
120 Gotfredsen JL, Hoppe C, Andersen R, Effects of substitution dietary guidelines targeted at prevention of IHD on dietary intake and risk factors in middle-aged Danish adults: the Diet and Prevention of Ischemic Heart Disease: a Translational Approach (DIPI) randomised controlled trial. Br J Nutr. Oct 28 2021;126(8):1179–1193. doi:10.1017/S0007114520005164 33357247
121 Hennein R, Liu C, McKeown NM, Increased Diet Quality is Associated with Long-Term Reduction of Abdominal and Pericardial Fat. Article. Obesity. 2019;27(4):670–677.30825267
122 Hodge AM, Karim MN, Hebert JR, Shivappa N, Milne RL, e Courten B. Diet scores and prediction of general and abdominal obesity in the Melbourne collaborative cohort study. Public Health Nutr. Apr 20 2021:1–12.
123 Huo Y, Cao S, Liu J, The Association between Plant-Based Diet Indices and Metabolic Syndrome in Chinese Adults: Longitudinal Analyses from the China Health and Nutrition Survey. Nutrients. Mar 9 2023;15(6)doi:10.3390/nu15061341
124 Jenkins DJA, Boucher BA, Ashbury FD, Effect of Current Dietary Recommendations on Weight Loss and Cardiovascular Risk Factors. J Am Coll Cardiol. Mar 7 2017;69(9):1103–1112.28254171
125 Jennings A, Mulligan AA, Khaw KT, Luben RN, Welch AA. A Mediterranean Diet Is Positively Associated with Bone and Muscle Health in a Non-Mediterranean Region in 25,450 Men and Women from EPIC-Norfolk. Nutrients. Apr 21 2020;12(4)
126 Johns DJ, Lindroos AK, Jebb SA, Sjostrom L, Carlsson LM, Ambrosini GL. Dietary patterns, cardiometabolic risk factors, and the incidence of cardiovascular disease in severe obesity. Obesity (Silver Spring). May 2015;23(5):1063–70.25865622
127 Jung S, Park S. Positive association of unhealthy plant-based diets with the incidence of abdominal obesity in Korea: a comparison of baseline, most recent, and cumulative average diets. Epidemiol Health. 2022;44:e2022063. doi:10.4178/epih.e2022063 35940180
128 Kanerva N, Harald K, Mannisto S, Adherence to the healthy Nordic diet is associated with weight change during 7 years of follow-up. Br J Nutr. Jul 2018;120(1):101–110.29936927
129 Kang M, Boushey CJ, Shvetsov YB, Changes in diet quality and body weight over 10 years: the Multiethnic Cohort Study. Br J Nutr. Jan 14 2021:1–9.
130 Khoury N, Gomez-Donoso C, Martinez MA, Associations Between the Modified Food Standard Agency Nutrient Profiling System Dietary Index and Cardiovascular Risk Factors in an Elderly Population. Front Nutr. 2022;9:897089. doi:10.3389/fnut.2022.897089 35967785
131 Kim H, Lee K, Rebholz CM, Kim J. Plant-based diets and incident metabolic syndrome: Results from a South Korean prospective cohort study. PLoS Med. Nov 2020;17(11):e1003371.33206633
132 Konieczna J, Morey M, Abete I, Contribution of ultra-processed foods in visceral fat deposition and other adiposity indicators: Prospective analysis nested in the PREDIMED-Plus trial. Clinical Nutrition. 2021;40(6):4290–4300.33610419
133 Konieczna J, Yanez A, Monino M, Longitudinal changes in Mediterranean diet and transition between different obesity phenotypes. Clin Nutr. Apr 20 2019;
134 Li Y, Roswall N, Strom P, Sandin S, Adami HO, Weiderpass E. Mediterranean and Nordic diet scores and long-term changes in body weight and waist circumference: results from a large cohort study. Br J Nutr. Dec 28 2015;114(12):2093–102.26458747
135 Li P, Zhang M, Zhu Y, Dietary patterns and changes in cardiovascular risk factors in apparently healthy Chinese women: a longitudinal study. J Clin Biochem Nutr. May 2016;58(3):232–9.27257349
136 Li M, Shi Z. Ultra-Processed Food Consumption Associated with Overweight/Obesity among Chinese Adults—Results from China Health and Nutrition Survey 1997–2011. Nutrients. 2021;13(8):2796.34444957
137 Li Y, Yatsuya H, Wang C, Dietary Patterns Derived from Reduced Rank Regression Are Associated with the 5-Year Occurrence of Metabolic Syndrome: Aichi Workers' Cohort Study. Nutrients. Jul 22 2022;14(15)doi:10.3390/nu14153019
138 Lim CGY, Whitton C, Rebello SA, van Dam RM. Diet Quality and Lower Refined Grain Consumption are Associated With Less Weight Gain in a Multi-Ethnic Asian Adult Population. J Nutr. Aug 7 2021;151(8):2372–2382.33978192
139 Lima ST, Silva Nalin de Souza B, Franca AK, Salgado Filho N, Sichieri R. Dietary approach to hypertension based on low glycaemic index and principles of DASH (Dietary Approaches to Stop Hypertension): a randomised trial in a primary care service. Br J Nutr. Oct 2013;110(8):1472–9.23632203
140 Liu T, Yang X, Wu Y, Unhealthy Dietary Patterns Increased Risks of Incident Obesity: A Prospective Cohort Study in Southwest China. Diabetes Metab Syndr Obes. 2022;15:3111–3120. doi:10.2147/DMSO.S377901 36237967
141 Liu X, Wan X, Zhang L, The sulfur microbial diet and increased risk of obesity: Findings from a population-based prospective cohort study. Clin Nutr. 2023;42(5)doi:10.1016/j.clnu.2023.03.011
142 Livingstone KM, Brayner B, Celis-Morales C, Ward J, Mathers JC, Bowe SJ. Dietary patterns, genetic risk, and incidence of obesity: Application of reduced rank regression in 11,735 adults from the UK Biobank study. Prev Med. May 2022;158:107035. doi:10.1016/j.ypmed.2022.107035 35346749
143 Livingstone KM, Milte C, Bowe SJ, Associations between three diet quality indices, genetic risk and body composition: A prospective cohort study. Clin Nutr. 2022;41(9)doi:10.1016/j.clnu.2022.07.005
144 Luo Y, Wang J, Sun L, Isocaloric-restricted Mediterranean Diet and Chinese Diets High or Low in Plants in Adults With Prediabetes. J Clin Endocrinol Metab. Jul 14 2022;107(8):2216–2227. doi:10.1210/clinem/dgac303 35579171
145 Maruyama C, Shijo Y, Kameyama N, Effects of Nutrition Education Program for the Japan Diet on Serum LDL-Cholesterol Concentration in Patients with Dyslipidemia: A Randomized Controlled Trial. J Atheroscler Thromb. Oct 1 2021;28(10):1035–1051. doi:10.5551/jat.60376 33455975
146 Maskarinec G, Namatame LA, Kang M, Differences in the association of diet quality with body fat distribution between men and women. Eur J Clin Nutr. Oct 2020;74(10):1434–1441.31980746
147 Maskarinec G, Lim U, Jacobs S, Diet Quality in Midadulthood Predicts Visceral Adiposity and Liver Fatness in Older Ages: The Multiethnic Cohort Study. Obesity (Silver Spring). Aug 2017;25(8):1442–1450.28745024
148 Mattei J, Sotos-Prieto M, Bigornia SJ, Noel SE, Tucker KL. The Mediterranean Diet Score Is More Strongly Associated with Favorable Cardiometabolic Risk Factors over 2 Years Than Other Diet Quality Indexes in Puerto Rican Adults. J Nutr. Apr 2017;147(4):661–669.28275099
149 Mendonca RD, Pimenta AM, Gea A, Ultraprocessed food consumption and risk of overweight and obesity: the University of Navarra Follow-Up (SUN) cohort study. Am J Clin Nutr. Nov 2016;104(5):1433–1440.27733404
150 Mirmiran P, Moslehi N, Golzarand M, Azizi F. Ultra-processed foods consumption and the risk of metabolically unhealthy phenotype in normal-weight and overweight/obese adults: a prospective investigation. Int J Food Sci Nutr. 2023;74(4):522–531. doi:10.1080/09637486.2023.2222935 37334484
151 Mirmiran P, Bahadoran Z, Vakili AZ, Azizi F. Western dietary pattern increases risk of cardiovascular disease in Iranian adults: a prospective population-based study. Appl Physiol Nutr Metab. Mar 2017;42(3):326–332.28177742
152 Mirmiran P, Moslehi N, Mahmoudof H, Sadeghi M, Azizi F. A Longitudinal Study of Adherence to the Mediterranean Dietary Pattern and Metabolic Syndrome in a Non-Mediterranean Population. Int J Endocrinol Metab. Jul 2015;13(3):e26128.26425127
153 Murphy KJ, Dyer KA, Hyde B, Long-Term Adherence to a Mediterranean Diet 1-Year after Completion of the MedLey Study. Nutrients. Jul 28 2022;14(15)doi:10.3390/nu14153098
154 Olstad DL, Lamb KE, Thornton LE, Prospective associations between diet quality and body mass index in disadvantaged women: the Resilience for Eating and Activity Despite Inequality (READI) study. Int J Epidemiol. Oct 1 2017;46(5):1433–1443.28398554
155 Otto MC, Padhye NS, Bertoni AG, Jacobs DR, Jr., Mozaffarian D. Everything in Moderation--Dietary Diversity and Quality, Central Obesity and Risk of Diabetes. PLoS One. 2015;10(10):e0141341. doi:10.1371/journal.pone.0141341 26517708
156 Pattinson AL, Seimon RV, Grech A, Diet quality following meal replacement vs food-based weight loss diets in postmenopausal women with obesity: a secondary analysis of TheTEMPO Diet Trial. Journal: Conference Abstract. Obesity reviews. 2020;21(SUPPL 1)
157 Pavić E, Hadžiabdić MO, Mucalo I, Effect of the Mediterranean diet in combination with exercise on metabolic syndrome parameters: 1-year randomized controlled trial. Journal Article; Randomized Controlled Trial. International journal for vitamin and nutrition research Internationale Zeitschrift fur Vitamin- und Ernahrungsforschung Journal international de vitaminologie et de nutrition. 2019;89(3–4):132–143.31322480
158 Perala MM, von Bonsdorff MB, Mannisto S, The healthy Nordic diet predicts muscle strength 10 years later in old women, but not old men. Age Ageing. Jul 1 2017;46(4):588–594.28338859
159 Poulsen SK, Crone C, Astrup A, Larsen TM. Long-term adherence to the New Nordic Diet and the effects on body weight, anthropometry and blood pressure: a 12-month follow-up study. Eur J Nutr. Feb 2015;54(1):67–76.24664189
160 Pribisalić A, Popović R, Salvatore FP, The role of socioeconomic status in adherence to the mediterranean diet and body mass index change: A follow-up study in the general population of southern croatia. Article. Nutrients. 2021;13(11)doi:10.3390/nu13113802
161 Rauber F, Chang K, Vamos EP, Ultra-processed food consumption and risk of obesity: a prospective cohort study of UK Biobank. Eur J Nutr. Jun 2021;60(4):2169–2180.33070213
162 Reidlinger DP, Darzi J, Hall WL, Seed PT, Chowienczyk PJ, Sanders TA. How effective are current dietary guidelines for cardiovascular disease prevention in healthy middle-aged and older men and women? A randomized controlled trial. Am J Clin Nutr. May 2015;101(5):922–30.25787998
163 Riboldi BP, Luft VC, Bracco PA, The inflammatory food index and its association with weight gain and incidence of diabetes: Longitudinal Study of Adult Health (ELSA-Brasil). Nutr Metab Cardiovasc Dis. 2022;doi:10.1016/j.numecd.2021.12.022
164 Roswall N, Angquist L, Ahluwalia TS, Association between Mediterranean and Nordic diet scores and changes in weight and waist circumference: influence of FTO and TCF7L2 loci. Am J Clin Nutr. Oct 2014;100(4):1188–97.25099543
165 Rudakoff LCS, Magalhaes E, Viola P, Ultra-processed food consumption is associated with increase in fat mass and decrease in lean mass in Brazilian women: A cohort study. Front Nutr. 2022;9:1006018. doi:10.3389/fnut.2022.1006018 36313106
166 San-Cristobal R, Navas-Carretero S, Livingstone KM, Mediterranean Diet Adherence and Genetic Background Roles within a Web-Based Nutritional Intervention: The Food4Me Study. Nutrients. Oct 11 2017;9(10)
167 Satija A, Malik V, Rimm EB, Sacks F, Willett W, Hu FB. Changes in intake of plant-based diets and weight change: results from 3 prospective cohort studies. Am J Clin Nutr. Sep 1 2019;110(3):574–582.31127828
168 Shakeri Z, Mirmiran P, Khalili-Moghadam S, Hosseini-Esfahani F, Ataie-Jafari A, Azizi F. Empirical dietary inflammatory pattern and risk of metabolic syndrome and its components: Tehran Lipid and Glucose Study. Article. Diabetology and Metabolic Syndrome. 2019;11(1)
169 Sidahmed E, Cornellier ML, Ren J, Development of exchange lists for Mediterranean and Healthy Eating diets: implementation in an intervention trial. J Hum Nutr Diet. Oct 2014;27(5):413–25.24112099
170 Steffen LM, Van Horn L, Daviglus ML, A modified Mediterranean diet score is associated with a lower risk of incident metabolic syndrome over 25 years among young adults: the CARDIA (Coronary Artery Risk Development in Young Adults) study. Br J Nutr. Nov 28 2014;112(10):1654–61.25234439
171 Sweetman AK, Carter J, Perez-Cornago A, Gao M, Jebb SA, Piernas C. Dietary pattern adherence in association with changes in body composition and adiposity measurements in the UK Biobank study. Obes Res Clin Pract. May-Jun 2023;17(3):233–241. doi:10.1016/j.orcp.2023.05.008 37230811
172 Tabung FK, Satija A, Fung TT, Clinton SK, Giovannucci EL. Long-term change in both dietary insulinemic and inflammatory potential is associated with weight gain in adult women and men. Article. Journal of Nutrition. 2019;149(5):804–815.31004153
173 Tobias DK, Zhang C, Chavarro J, Healthful dietary patterns and long-term weight change among women with a history of gestational diabetes mellitus. Int J Obes (Lond). Nov 2016;40(11):1748–1753.27569683
174 Turner-McGrievy GM, Davidson CR, Wingard EE, Wilcox S, Frongillo EA. Comparative effectiveness of plant-based diets for weight loss: a randomized controlled trial of five different diets. Nutrition. Feb 2015;31(2):350–8.25592014
175 Tussing-Humphreys L, Lamar M, McLeod A, Effect of Mediterranean diet and Mediterranean diet plus calorie restriction on cognition, lifestyle, and cardiometabolic health: A randomized clinical trial. Article. Preventive Medicine Reports. 2022;29doi:10.1016/j.pmedr.2022.101955
176 Um CY, Hodge RA, McCullough ML. Change in Diet Quality and Meal Sources during the COVID-19 Pandemic in a Diverse Subset of Men and Women in the Cancer Prevention Study-3. Nutrients. Feb 7 2023;15(4)doi:10.3390/nu15040849
177 Van Horn L, Aragaki AK, Howard BV, Eating Pattern Response to a Low-Fat Diet Intervention and Cardiovascular Outcomes in Normotensive Women: The Women's Health Initiative. Curr Dev Nutr. Mar 2020;4(3):nzaa021. doi:10.1093/cdn/nzaa021 32159070
178 Vinke PC, Navis G, Kromhout D, Corpeleijn E. Age- and Sex-Specific Analyses of Diet Quality and 4-Year Weight Change in Nonobese Adults Show Stronger Associations in Young Adulthood. J Nutr. Mar 1 2020;150(3):560–567.31687774
179 Wang T, Heianza Y, Sun D, Improving adherence to healthy dietary patterns, genetic risk, and long term weight gain: gene-diet interaction analysis in two prospective cohort studies. Bmj. Jan 10 2018;360:j5644.29321156
180 Winkvist A, Klingberg S, Nilsson LM, Longitudinal 10-year changes in dietary intake and associations with cardio-metabolic risk factors in the Northern Sweden Health and Disease Study. Nutr J. Mar 28 2017;16(1):20.28351404
181 Xu X, Shi Z, Liu G, The Joint Effects of Diet and Dietary Supplements in Relation to Obesity and Cardiovascular Disease over a 10-Year Follow-Up: A Longitudinal Study of 69,990 Participants in Australia. Nutrients. Mar 15 2021;13(3)
182 Yang J, Zhang C, Chavarro JE, Lifestyle Changes and Long-term Weight Gain in Women With and Without a History of Gestational Diabetes Mellitus: A Prospective Study of 54,062 Women in the Nurses' Health Study II. Diabetes Care. Feb 1 2022;45(2):348–356. doi:10.2337/dc21-1692 34880065
183 Assaf-Balut C, Garcia de la Torre N, Duran A, A Mediterranean diet with an enhanced consumption of extra virgin olive oil and pistachios improves pregnancy outcomes in women without gestational diabetes mellitus: a sub-analysis of the St. Carlos gestational diabetes mellitus prevention study. Ann Nutr Metab. 2019;74(1):69–79. doi:10.1159/000495793 30554220
184 Dodd JM, Deussen AR, Louise J. A Randomised Trial to Optimise Gestational Weight Gain and Improve Maternal and Infant Health Outcomes through Antenatal Dietary, Lifestyle and Exercise Advice: The OPTIMISE Randomised Trial. Nutrients. Dec 2 2019;11(12)
185 Van Horn L, Peaceman A, Kwasny M, Dietary Approaches to Stop Hypertension Diet and Activity to Limit Gestational Weight: Maternal Offspring Metabolics Family Intervention Trial, a Technology Enhanced Randomized Trial. Am J Prev Med. Nov 2018;55(5):603–614. doi:10.1016/j.amepre.2018.06.015 30262148
186 Hillesund ER, Bere E, Haugen M, Overby NC. Development of a New Nordic Diet score and its association with gestational weight gain and fetal growth - a study performed in the Norwegian Mother and Child Cohort Study (MoBa). Public Health Nutr. Sep 2014;17(9):1909–18. doi:10.1017/S1368980014000421 24685309
187 Rifas-Shiman SL, Rich-Edwards JW, Kleinman KP, Oken E, Gillman MW. Dietary quality during pregnancy varies by maternal characteristics in Project Viva: a US cohort. J Am Diet Assoc. Jun 2009;109(6):1004–11. doi:10.1016/j.jada.2009.03.001 19465182
188 Tielemans MJ, Erler NS, Leermakers ET, A priori and a posteriori dietary patterns during pregnancy and gestational weight gain: The Generation R study. Nutrients. Nov 12 2015;7(11):9383–99. doi:10.3390/nu7115476 26569303
189 Hrolfsdottir L, Halldorsson TI, Birgisdottir BE, Hreidarsdottir IT, Hardardottir H, Gunnarsdottir I. Development of a dietary screening questionnaire to predict excessive weight gain in pregnancy. Matern Child Nutr. Jan 2019;15(1):e12639. doi:10.1111/mcn.12639 30033533
190 Wei X, He JR, Lin Y, The influence of maternal dietary patterns on gestational weight gain: A large prospective cohort study in China. Nutrition. Mar 2019;59:90–95. doi:10.1016/j.nut.2018.07.113 30471529
191 Ancira-Moreno M, Vadillo-Ortega F, Rivera-Dommarco JA, Gestational weight gain trajectories over pregnancy and their association with maternal diet quality: Results from the PRINCESA cohort. Nutrition. Sep 2019;65:158–166. doi:10.1016/j.nut.2019.02.002 31132630
192 Yong HY, Mohd Shariff Z, Mohd Yusof BN, Pre-Pregnancy BMI influences the association of dietary quality and gestational weight gain: The SECOST study. Int J Environ Res Public Health. Oct 4 2019;16(19)doi:10.3390/ijerph16193735
193 Hillesund ER, Bere E, Sagedal LR, Pre-pregnancy and early pregnancy dietary behavior in relation to maternal and newborn health in the Norwegian Fit for Delivery study - a post hoc observational analysis. Food Nutr Res. 2018;62doi:10.29219/fnr.v62.1273
194 Li Y, Zhou X, Zhang Y, Association of Maternal Dietary Patterns With Birth Weight and the Mediation of Gestational Weight Gain: A Prospective Birth Cohort. Front Nutr. 2021;8:782011. doi:10.3389/fnut.2021.782011 34901129
195 Liu EF, Zhu Y, Ferrara A, Hedderson MM. Dietary Quality Indices in Early Pregnancy and Rate of Gestational Weight Gain among a Prospective Multi-Racial and Ethnic Cohort. Nutrients. Feb 6 2023;15(4)doi:10.3390/nu15040835
196 Berube LT, Deierlein AL, Woolf K, Messito MJ, Gross RS. Prenatal Dietary Patterns and Associations With Weight-Related Pregnancy Outcomes in Hispanic Women With Low Incomes. Child Obes. May 2 2023;doi:10.1089/chi.2022.0227
197 Yang M, Feng Q, Chen C, Healthier diet associated with reduced risk of excessive gestational weight gain: A Chinese prospective cohort study. Matern Child Nutr. Jul 12 2022:e13397. doi:10.1111/mcn.13397 35821659
198 Acosta-Manzano P, Acosta FM, Coll-Risco I, The Influence of Exercise, Lifestyle Behavior Components, and Physical Fitness on Maternal Weight Gain, Postpartum Weight Retention, and Excessive Gestational Weight Gain. Int J Sport Nutr Exerc Metab. Nov 1 2022;32(6):425–438. doi:10.1123/ijsnem.2021-0201 35894919
199 Jayedi A, Zeraattalab-Motlagh S, Moosavi H, Mirmohammadkhani M, Emadi A, Shab-Bidar S. Association of plant-based dietary patterns in first trimester of pregnancy with gestational weight gain: results from a prospective birth cohort. Eur J Clin Nutr. Feb 14 2023;77(6):660–667. doi:10.1038/s41430-023-01275-x 36788355
200 Radwan H, Hashim M, Hasan H, Adherence to the Mediterranean diet during pregnancy is associated with lower odds of excessive gestational weight gain and postpartum weight retention: results of the Mother-Infant Study Cohort. Br J Nutr. Oct 14 2022;128(7):1401–1412. doi:10.1017/S0007114521002762 34294166
201 Itani L, Radwan H, Hashim M, Dietary patterns and their associations with gestational weight gain in the United Arab Emirates: results from the MISC cohort. Nutr J. Apr 21 2020;19(1):36. doi:10.1186/s12937-020-00553-9 32316972
202 Jarman M, Mathe N, Ramazani F, Dietary Patterns Prior to Pregnancy and Associations with Pregnancy Complications. Nutrients. Jul 17 2018;10(7)doi:10.3390/nu10070914
203 Cummings JR, Lipsky LM, Schwedhelm C, Liu A, Nansel TR. Associations of ultra-processed food intake with maternal weight change and cardiometabolic health and infant growth. Int J Behav Nutr Phys Act. May 26 2022;19(1):61. doi:10.1186/s12966-022-01298-w 35619114
204 Hu J, Gao M, Ma Y, The Association between Dietary Patterns and Pre-Pregnancy BMI with Gestational Weight Gain: The "Born in Shenyang" Cohort. Nutrients. Jun 20 2022;14(12)doi:10.3390/nu14122551
205 Alves-Santos NH, Cocate PG, Eshriqui I, Dietary patterns and their association with adiponectin and leptin concentrations throughout pregnancy: a prospective cohort. British Journal of Nutrition. 2018;119(3):320–329.29345609
206 Silva-del Valle MA, Sanchez-Villegas A, Serra-Majem L. Association between the adherence to the Mediterranean diet and overweight and obesity in pregnant women in Gran Canaria. Nutr Hosp. May-Jun 2013;28(3):654–9. doi:10.3305/nh.2013.28.3.6377 23848085
207 Boghossian NS, Yeung EH, Lipsky LM, Poon AK, Albert PS. Dietary patterns in association with postpartum weight retention. Am J Clin Nutr. Jun 2013;97(6):1338–45. doi:10.3945/ajcn.112.048702 23576044
208 Li N, Su X, Liu T, Dietary patterns of Chinese puerperal women and their association with postpartum weight retention: Results from the mother-infant cohort study. Matern Child Nutr. Jan 2021;17(1):e13061.33135839
209 Ostbye T, Peterson BL, Krause KM, Swamy GK, Lovelady CA. Predictors of postpartum weight change among overweight and obese women: results from the Active Mothers Postpartum study. J Womens Health (Larchmt). Feb 2012;21(2):215–22. doi:10.1089/jwh.2011.2947 22092110
210 Stendell-Hollis NR, Thompson PA, West JL, Wertheim BC, Thomson CA. A comparison of Mediterranean-style and MyPyramid diets on weight loss and inflammatory biomarkers in postpartum breastfeeding women. J Womens Health (Larchmt). Jan 2013;22(1):48–57. doi:10.1089/jwh.2012.3707 23276189
211 Wiltheiss GA, Lovelady CA, West DG, Brouwer RJ, Krause KM, Ostbye T. Diet quality and weight change among overweight and obese postpartum women enrolled in a behavioral intervention program. J Acad Nutr Diet. Jan 2013;113(1):54–62. doi:10.1016/j.jand.2012.08.012 23146549
212 Augustin H, Winkvist A, Bärebring L. Poor Dietary Quality is Associated with Low Adherence to Gestational Weight Gain Recommendations among Women in Sweden. Nutrients. Jan 25 2020;12(2)doi:10.3390/nu12020317