# Results

## Literature search and screening results

The literature search (Appendix 4 ) yielded 27,952 search results after the removal of duplicates (see Figure 2). Dual-screening resulted in the exclusion of 23,804 titles, 2750 abstracts, and 1298 full-texts articles. Reasons for full-text exclusion are in Appendix 5: Excluded articles. The body of evidence includes 212 articles published since January 1980 in infants and young children up to age 24 months (n=18^1–18^) and children and adolescents (n=62 ^2,10,11,15,19–76^), since January 2014 in adults and older adults (n=106^77–182^), and since January 2000 in individuals during pregnancy (n=25^183–206^), and individuals during postpartum (n=7) articles.^198,203,207–212^ In addition, this review updates graded conclusion statements from existing reviews that were based in 38 articles in adults and older adults.^†^

† Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

Figure 2 Literature search and screen flow chart.

Literature search and screening flow chart

## Infants and young children up to age 24 months

Eighteen articles met inclusion criteria and were published between January 1980 and May 2023 examining the relationship between dietary patterns consumed from birth up to 24 months of age and growth, body composition, and risk of obesity.^1–18^ Study designs include 1 randomized controlled trial (RCT) and 17 prospective cohort studies (Table 6).

### Description of the evidence

#### Population

Sample size of study groups ranged from N=68 up to N=14989. Studies were conducted in 9 different countries: Australia; Brazil; China; Columbia; Norway; Scotland; The Netherlands; the United Kingdom and the United States or Puerto Rico. Multiple articles from the following cohorts were included: Infant Feeding Practices Study II (IFPS II), Generation R Study, and Southampton Women’s Survey, but the articles examined different dietary patterns or dietary patterns at different ages.

Studies examined dietary patterns consumed at ages ranging from birth up to 2 years, but most (14 of 18) examined dietary patterns at age 6 months or between 6 and 12 months. Seven articles reported some information on the racial or ethnic background of participants as follows: 1) 4% non-white; 2) 91% White, 1% African American, 3% Hispanic, 3% Asian/Pacific Islander; 3) 71% “white skin color”; 4) 94% White; 5) 67% Dutch; 6) 90% White non-Hispanic; 7) ~41% Hispanic, 29% Non-Hispanic White, 25% Non-Hispanic Black, and 6% Non-Hispanic Other. Three studies exclusively enrolled those with low socioeconomic position (SEP), e.g., based on Special Supplemental Nutrition Program for Women, Infants, and Children (WIC) participation.^3,4,12^

#### Intervention/exposure and comparator

Studies used a variety of diet assessment methods, with studies using a food-frequency questionnaire most frequently, 24-hour recalls, and/or caregiver surveys/questionnaires. Most of the studies (13 of 18) collected diet at more than one time point, except for five articles that used a single baseline assessment. Analytic approaches used to investigate dietary patterns included:

- Investigator-assigned dietary intervention^12^
- A priori Index/Score derivation ^2,3,7,10,16,17,43^
- Factor/cluster or latent-class analysis^1,5–9,11,13–15,17,18^
- Reduced rank regression analysis^17^

#### Outcomes

Most (16 of 18) articles reported using standardized protocols, instruments, and trained staff to measure weight, height, and/or waist circumference of participants. However, precise cutoffs and/or methods used to categorize or classify participants based on BMI percentile, BMI z-score, or other weight-relative-to-height ratios varied across studies (e.g., CDC vs. WHO vs. Cole's method (https://www.scopus.com/record/display.uri?eid=2-s2.0-0034611996&origin=inward)). The following outcomes were reported across the body of evidence:

- BMI and/or WLZ ^1,3–18,43^
- Body composition (e.g., fat mass) ^5,7,9–13,15,17^
- Weight and/or height/length^5,9,10,12,14,18^
- Risk of overweight and/or obesity ^1,142^
- Head circumference^12^

### Synthesis of the evidence

Eight articles reported no statistically significant association between the dietary patterns consumed between 6 months up to age 24 months and outcomes of growth, body composition, and risk of obesity outcomes (at 12 months up to 11 years) were reported in 8 articles.^1–3,6,10,12,15,16^ Most of these dietary patterns included vegetables and fruit but varied considerably in other components, such as human milk/infant formula, cereals/grains (rice, pasta) and sources of protein and/or iron (e.g., meat, fish, beans). The studies also varied considerably in which outcome measure(s) were evaluated and the ages at follow-up. Across the body of evidence, some components were not further defined, such as ‘baby snacks’, ‘textured foods’, or ‘home-prepared foods’. Because the types and proportions of components in a dietary pattern during the complementary feeding period are likely to change over that developmental window, it was difficult to collate findings across this age group (e.g., birth to 5 months, at age 6 months, 8 to 11 months, at age 14 months, from 19 to 24 months). Several studies examined dietary patterns relative to alignment with the standard complementary feeding guidelines at the time of the study. However, these recommendations varied over time and between countries.

There was substantial heterogeneity in direction and magnitude among the studies that reported any statistically significant dietary pattern/outcome associations.^4,5,8–11,13–16,18^, the direction and magnitude of results varied. A few studies found that dietary patterns consumed at ages 6 months and up to 12 months that emphasized human milk and/or infant formula, vegetables, and fruit were significantly associated with lower BMI z-scores or greater lean mass at age 4 years, lower fat mass at age 6 years, and smaller waist circumference age 7 years.^4,7,11,13^ Notably, these dietary patterns varied in other components and the magnitude of findings were relatively small. In addition, these studies also reported no significant associations when examining dietary patterns consumed at other ages or in relation to other outcomes.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee did not develop conclusion statements to answer the question, “What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?”, because studies were highly variable and could not be aligned based on the dietary patterns consumed between birth and age 24 months and outcomes examined (see Table 5).

Table 5 Conclusion statement and grade for dietary patterns consumed by infants and young children up to age 24 months and growth, body composition, and risk of obesity

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by infants and young children up to age 24 months and growth, body composition, and risk of obesity because of substantial concerns with consistency.
Grade | Grade not assignable
Body of Evidence | 18 articles: 1 randomized controlled trial, 17 prospective cohort studies
Rationale | Critical limitations across the body of evidence prevented the ability to draw a conclusion. These issues included highly variable studies in terms of exposure and outcome assessment methods and timing, methods used, and outcome reporting. These may in part explain the substantial heterogeneity in the direction and magnitude of effect estimates between dietary patterns and outcomes. Some concerns were identified with risk of bias in the individual studies, including important confounders that were not accounted for. Most studies directly examined the relationship of interest. Relative to the U.S. population, the dietary patterns examined, other infant and toddler feeding practices, and some participant characteristics may be less generalizable.

A conclusion could not be drawn because of substantial variation across studies in terms of the measures and timing dietary pattern exposure assessment in relation to growth, body composition, and obesity outcomes. This lack of alignment across studies on these factors undermined the ability to summarize the evidence. Although a grade could not be assigned, critical limitations were identified in the consistency of effects across the body of evidence. Risk of bias concerns were identified across the individual studies that included insufficient adjustment for important confounding factors and missing data that were not accounted for (see Table 7 and Table 8). In particular, the race and/or ethnicity of participants was not reported or adjusted for and many (11 of 19) studies had moderate-high attrition rates over follow-up period of interest. Many studies directly examined the relationship between dietary pattern consumption from birth up to 2 years of age and growth, body composition, and risk of obesity outcomes. The body of evidence included studies from a total of 9 countries, with 5 of the articles from studies that were conducted in the United States. Relative to the U.S. population (at birth to 24 months), the specific dietary patterns examined at specific ages may be less generalizable. This body of evidence includes both large and small studies (with significant as well as null findings) so publication bias may be less likely.

Table 6 Evidence in infants and young children up to age 24 months examining the relationship between dietary patterns consumed and growth, body composition and risk of obesity^a^

Study Characteristics | Intervention/exposure and comparator | Results | Methodological considerations
Abraham, 2012 ^1^; Scotland; Growing Up in Scotland (GUS) study (2005–2008); Analytic N=4493; Participant characteristics: NR; 4% non-white ethnic group (Bradshaw, 2007); Selection: Variables with >5% missing responses excluded from cluster analysis. Excluded infants with missing data points for models in Tables 2 and 3. | Age at Dietary Pattern:19 to 24 mo; [underlined: Cluster 1 (Negative)]: low fruit, vegetable; high sweets, crisps, soft drinks, snacking; [underlined: Cluster 2 (Positive):] high fruit, vegetable; low snacking; Method(s):Factor/Cluster | Age at Follow-up: 4y; OW/Ob frequency at 45–48mo: 12.5% vs. 11.9%, P=0.598, NS; Cluster 1 v. Cluster 2, ref & BMI z-score: 0.96, 95% CI: 0.76, 1.21 | - Did not account for: Sex, Age, Race and/or Ethnicity, Maternal age, or Birth size/gestational age; - Cannot determine whether groups were similar at baseline on key characteristics; - Cannot determine if outcome assessors were blinded, primary interviewers were unblinded;; - Bradshaw, 2007 summarizes Sweep 1 baseline characteristics; Funding: Growing Up in Scotland (GUS) data set received no specific grant from any funding agency in the public, commercial or not-for profit sector.
Agnihotri, 2021 ^2^; Norway; Norwegian Mother, Father and Child Cohort Study (MoBa); Analytic N=14989; Participant characteristics: 49.7% female; 30% ≤ 12y maternal education; Selection: Enrolled mothers during pregnancy; Excluded if missing data from Medical Birth Registry of Norway; missing questionnaire data during mother’s pregnancy; multiple pregnancies; additional pregnancies by same mother; extreme intake during pregnancy; child age <7 or >9.5 at outcome; missing outcome data; anthropometric data outside +/− 4SD | Age at Dietary Pattern: 6 mo, 18 mo; [underlined: New Nordic Diet (NND) score, 6mo]: Positive: homemade Fruit puree (v. commercial); homemade Dinners (v. commercial); homemade Porridge (v. commercial); Exclusive breast-fed ≥4 months; Any breast-fed at 6 mo; Water (v. sweetened beverages); [underlined: NND, 18 mo]: Positive: Vegetables >5.5 times/wk; Fruit >10.5 times/wk; Peas and beans >5 times/wk; Potatoes (more than rice/pasta); Porridge (more homemade than commercial); Fish >2.13 times/wk; Milk (more milk than juice); Water (more than sweetened beverages); Homemade food (more than commercial baby food); Method(s):Index or Score Analysis | Age at Follow-up: 8y; NND at 6 mo & Risk of OW; - Low, OR: 1.00, ref; - Medium, OR: 1.05, 95% CI: 0.93, 1.16; p-trend=0.402; - High, OR: 0.97, 95% CI: 0.83, 1.13; p-trend=0.724; - Per 1-pt, OR: 0.99, 95% CI: 0.96, 1.03; p-trend=0.773; NND at 18 mo & Risk of OW; - Low, OR: 1.00, ref; - Medium, OR: 0.96, 95% CI: 0.86, 1.08; p-trend=0.506; - High, OR: 0.99, 95% CI: 0.86, 1.14; p-trend=0.883; Per 1-pt, OR: 1.00, 95% CI: 0.97, 1.03; p-trend=0.916 | - Did not account for: Race/Ethnicity, Physical activity, Anthropometry (at 3 y and 7 y); or Energy intake in analyses; - BMI computed from parent-reported child Ht & Wt at 8 y; Funding: Norwegian Ministry of Health and Care Services, Ministry of Education and Research
Amaro-Rivera, 2019 ^3^; Puerto Rico; Analytic N=68; Participant characteristics: 46.8% female; 32.5% ≤ high school education in parents; SEP: Caregivers were WIC participants; Selection: Excluded non-singleton infants & toddlers; caregivers <21 years of age; those not participating in WIC program; infants & toddlers with major anomalies/disabilities that could impede regular feeding practices; infants age 6–7 mo | Age at Dietary Pattern: 0 to 24mo; [underlined: Dietary pattern (not named) at ages 0 to 5 months]: Positive for Milk (Exclusive Human Milk; Partial Human Milk; or Formula); Negative (if before age 6 mo): Grains or cereals; Proteins (meat or beans); Vegetables; Fruits; 100% fruit juices; Sugar-sweetened beverages; Sweets; Salty snacks; Method(s):Index or Score Analysis | Age at Follow-up: ~12 to 36 mo; WFL z-score, RR: 1.02, 95% CI: 0.98, 1.07 | - Did not account for: Race/Ethnicity, Physical activity; - Drop-out rates are very high. Unclear if the study had power to detect the difference; Funding: National Institute on Minority Health and Health Disparities, University of Puerto Rico Central Administration
Au, 2023 ^4^; United States; WIC Infant and Toddler Feeding Practices Study-2 (WIC ITFPS-2); Analytic N=2858; Participant characteristics: SEP: 90% were below poverty guideline; Race and/or Ethnicity: ~41% Hispanic; 29% Non-Hispanic White; 25% Non-Hispanic Black; 6% Non-Hispanic Other; Selection: Enrolled only WIC-participants (mothers >l6y old) | Age at Dietary Pattern: 7 to 12mo; [underlined: Infant Diet Quality Index (IDQI):] Positive: Duration HM-fed; Exclusivity of HM; Solids Age; iron-rich Cereals; Fruit (frequency); Vegetables (frequency); Fruit (different/variety); Vegetables (different/variety); Number of meals and snacks. Negative: Non-recommended bottle-feeding practices; Commercial baby food; Number of meals and snacks; Later introduction (at age 12 or 9mo): Cow milk; Sugar-sweetened beverages; Salty or sweet snacks; Other drinks or liquids (e.g., teas or broths); Textured foods; Method(s): Index or Score Analysis | Age at Follow-up: 2y and 4y; IDQI & BMIz at 2 y, β: −1.24; 95% CI: −2.01, −0.47; P=0.002; IDQI & BMIz at 4 y, β: −0.92; 95% CI: −1.53, −0.30; P=0.003 | - Did not account for: Physical activity; - Diet collected from repeat assessments of caregivers with one 24-hr recall and survey;; - Weight/Height measured at birth, 6mo, 1y, 2y, 3y, and 4y;; - Author-noted large effect sizes for BMIz; - Funding: NHLBI; USDA/NIFA
Baird, 2008 ^5^; United Kingdom; Southampton Women’s Survey (SWS); Analytic N=1740; Participant characteristics: 46.9% female; 94% white; Selection: Excluded multiples and preterm births | Age at Dietary Pattern: 6 mo; [underlined: ‘Infant Guidelines’]: high frequency of consumption of vegetables, fruit, meat, fish, home-prepared foods, breast milk; low frequency of consumption of commercial baby foods in jars and formula; [underlined: ‘Adult Foods’]: high frequency of consumption of bread, savory snacks, biscuits, squash, breakfast cereals, and crisps; low frequency of breast milk, baby rice, and cooked and canned fruit; Method(s): Factor/Cluster | Age at Follow-up: 12 mo; ‘Infant guidelines’; - Skinfold thickness (SFT); ○ 6–12mo: β: 0.11, 95% CI: 0.04, 0.18; P-value: 0.002; Q1 ref v. Q4: 0.26, 95% CI: 0.07, 0.45; ○ at 12mo: β: 0.13, 95%CI: 0.01, 0.25; p=0.03; - Length; ○ 6–12mo, SDS: β: 0.03, 95%CI: −0.04, 0.10; p=0.225; ○ at 12 mo, SDS: β: 0.04, 95% CI: −0.13, 0.21; p=0.612; - Weight; ○ 6–12 mo, SDS: β: 0.10, 95%CI: 0.04, 0.17; p=0.002;; ○ Q1 ref v. Q4: 0.24, 95% CI: 0.06, 0.43 (ie 0.12 kg, 95% CI: 0.02, 0.23); ○ at 12 mo, SDS: β: 0.07, 95% CI: −0.01, 0.14; p=0.09; ‘Adult foods’; - SFT; ○ 6–12mo: β: 0.00, 95% CI: −0.07, 0.07; p= 0.92; ○ at 12mo: β: 0.01, 95% CI: −0.12, 0.13; p=0.89; - Weight,; ○ 6–12 mo, SDS: β:−0.08, 95%CI: −0.15, −0.02; p=0.0015; ○ at 12 mo, SDS: β: 0.02, 95% CI: −0.06, 0.10; P=0.60; - Length,; ○ 6–12mo, SDS: β:−0.04, 95%CI: −0.11, 0.03; p=0.225; ○ at 12 mo; β: 0.00, 95% CI: −0.17, 0.17; p=0.984 | - Did not account for: Age, Race/ethnicity (94% White; ‘ethnic minorities under-represented’); Physical activity; SEP; or Maternal age; - Cannot determine whether groups were similar at baseline;; - Unclear whether outcome assessors were blinded to the infants’ feeding histories;; - BF duration and infant diet was retrospectively self-reported by mothers at 6 and 12mo, thus may have been biased; ethnic minorities were underrepresented in this sample.; - Funding: UK Medical Research Council; University of Southampton British Heart Foundation Food Standards Agency Dunhill Medical Trust
Bell, 2013 ^6^; Australia; NOURISH study and South Australian Infant Dietary Intake study (SAIDI); Analytic N=493; Participant characteristics: 54% female; Race/ethnicity NR; Selection: N/A | Age at Dietary Pattern: 14 mo; [underlined: “Core’:] fruit, grains, nonwhite bread, vegetables, cheese, eggs, nuts and seeds; [underlined: ‘Basic combination’]: basic core + non-core w/o fruit or vegetables; Method(s):Factor/Cluster | Age at Follow-up: 24mo; ‘Core’ & BMIz: 0.006, 95%CI: −0.128, 0.113; p=0.906; ‘Basic combination’ & BMIz: 0.029, 95% CI: −0.104, 0.180; p=0.603 | - Did not account for: Race/ethnicity; Birth size; Gestational age; - ‘Basic core’ and ‘Non-core’ patterns at age 24mo not shown were also reported for cross-sectional analyses; - Cannot determine whether groups differed at baseline on key characteristics;; - Cannot detrmined whether outcome assessors were blinded;; - Cannot determine reliability of outcome assessment, 17% of outcomes measured by general practitioners or child health nurses, not study staff;; - Mothers may have reported more favorable dietary intakes (highly educated sample who may have greater knowledge of dietary recommendations); - Funding: Meat and Livestock Australia, National Health and Medical Research Council of Australia, SA Health
Golley, 2013 ^7^; United Kingdom; Avon Longitudinal Study of Parents and Children; Analytic N=7834 at 7y; Participant characteristics: 48.3% female; Race/ethnicity NR; Selection: Excluded triplets and quadruplets | Age at Dietary Pattern: 6 mo; [underlined: CFUI score]: BF duration, feeding on demand, age of introduction to solids, exposure to iron-rich cereals, fruits, vegetables, protein foods variety, exposure to types of sugary drinks, exposure to confectionary, cakes, biscuits, savory snacks, timing of cow’s milk introduction, exposure to tea, timing of lumpy food introduction, number of daily meals and snacks. Higher CFUI scores reflected higher adherence to CF guidelines.; Method(s):Index or Score Analysis | Age at Follow-up: 7y; - BMI: β:−0.05, 95% CI: −0.12, 0.01; P-value: 0.13; - WC: β: −0.15, 95% CI: −0.31, −0.002), P=0.046 | - Did not account for: N/A; - Cannot determine validity/reliability of assessment for exposure;; - Cannot determine whether outcome assessors were blinded;; - Did not account for high attrition rate/lost to follow-up (44%); - Funding: UK and European Community’s Seventh Framework Programme; The UK Medical Research Council; Wellcome Trust; University of Bristol
Hohman, 2017 ^8^; United States; INSIGHT; Analytic N=291; Participant characteristics: ~47–51% girls; ~90% White, non-Hispanic, well-educated (~90% >=some college), higher income (~50% >75,000);; Selection: Babies born to primiparous mothers, who are healthy, term, singletons | Age at Dietary Pattern: 9 mo; [underlined: ‘BFV’]: Positive: Predominantly breastfed at 9 month, Fruits and vegetables; Negative: Fruit juice and high-energy-density (ED) foods like sweet drinks,sweet foods, and French fries; [underlined: ‘BLV’:] Positive: Predominantly breastfed at 9 months; Negative: Fruits and vegetables, and lower consumption of other age-appropriate complementary foods than BFV; [underlined: ‘FFV’]: Positive: Predominantly formula-fed at 9 months and consuming fruits and vegetables; Negative: low probability of consuming fruit juice and sweet drinks; [underlined: ‘FLV’]: Positive: Predominantly formula-fed at 9 months; Negative: Lower probability of consuming age-appropriate complementary foods and a higher probability of consuming fruit juice than the FFV class; [underlined: ‘FHED’:] Positive: high probability of being formula-fed at 9 months and consuming fruits and vegetables, fruit juice, sweet drinks, sweet foods, and French fries; Method(s):Factor/Cluster | Age at Follow-up: 2y; Mean BMI %-tile (SD); - BFV: 45.5 (30.7); - BLV: 68.5 (26.5); - FFV: 35.8 (25.3); - FLV: 51.3 (28.5); - FHED: 60.0 (26.7); - p-value: 0.0001; - BFV vs. BLV: p<0.05;; - BLV vs. FFV: p<0.05;; - FFV vs. FLV: p<0.05;; - FFV vs FHED: p<0.05; Mean BMI z-score %-tile (SD); - BFV: −0.15 (1.10); - BLV: 0.56 (0.90); - FFV: −0.42 (0.84); - FLV: 0.04 (0.94); - FHED: 0.34 (0.87); - p-value: 0.0006; - BFV v. BLV: p<0.05;; - BFV v. FHED: p<0.05;; - BLV v. FFV: p<0.05;; - FFV v. FHED: p<0.05 | - Did not account for: any key confounders (from RCT) except sex, which was shown to be NS; Funding: NIDDK/NIH; USDA; The Penn State Clinical & Transitional Research Institute
Jin, 2022 ^9^; China; Longitudinal Twin Study (LoTiS); Analytic N=173 pairs of twins @ 1y; N=151 pairs of twins @ 2y; Participant characteristics: 45.4% Female; Race/ethnicity: NR; SEP: NR; Preterm delivery: 53.2; Selection: Twins study; Excluded those LFU; Cotwins with congenital malformation were excluded | Age at Dietary Pattern: 6 to 12mo; [underlined: ‘Tuber-and meat’:] high intakes of tubers, meats, cereals, and biscuits; [underlined: ‘Vegetable and fruit’]: high intakes of vegetables, fruits, and drinks; Method(s):Factor/Cluster | Age at Follow-up: 12mo and 24mo; ‘Tuber-and meat’, Q1 v. Q4 β (SD); - FM @12mo, 1.22 (0.48) v. 1.21 (0.49); p=0.937; - % FM @ 12mo, 14.48 (0.66) v. 13.44 (0.67); p=0.603; - FM @ 24mo, 1.65 (0.60) v. 1.59 (0.53); p=0.597; - %FM @ 24mo, 14.09 (0.62) v. 13.61 (0.62); p=0.833; - WAZ @12 mo, 0.01 (0.92) v. −0.01 (0.91); p =0.949; - HAZ @12 mo, −0.12 (0.94) v. 0.07 (1.09); p =0.233; - BAZ @12 mo, 0.11 (0.84) v. p:−0.04 (0.84); p =0.250; - WAZ @ 24mo, −0.23 (0.71) v. −0.21 (0.87); p =0.908; - HAZ @ 24mo, −0.49 (0.72) v. −0.38 (1.07); p =0.482; - BAZ @ 24mo, 0.09 (0.71) v. 0.02 (0.81); p =0.575; - Weight (6–12mo), 1.26 (0.42) v. 1.42 (0.56); p=0.026; - Weight (12–24mo), 2.34 (0.52) v. 2.43 (0.76); p=0.432; ‘Vegetable and fruit’, Q1 v. Q4 β (SD); - FM @ 12mo, 1.34 (0.48) v. 1.27 (0.50); p=0.512; - % FM @ 12mo 13.35 (0.70) v. 13.30 (0.61); p=0.963; - FM @ 24mo 1.68 (0.65) v. 1.57 (0.58); p=0.476; - %FM @ 24mo, 14.19 (0.65) v. 13.58 (0.78); p=0.946; - WAZ @12mo, 0.05 (0.89) v. −0.01 (0.93); p=0.652; - HAZ @12mo, −0.11 (1.08) v. −0.14 (1.15); p =0.857; - BAZ @12mo, 0.16 (0.79) v. 0.10 (0.81); p =0.587; - WAZ @ 24mo, −0.26 (0.86) v. −0.20 (0.93); p =0.714; - HAZ @ 24mo, −0.49 (1.03) v. −0.57 (0.97); p =0.602; - BAZ @ 24mo, 0.05 (0.67) v. 0.20 (0.84); p =0.231; - Weight (6–12mo), 1.34 (0.52) v. 1.32 (0.49); p=0.847; - Weight (12–24mo): 2.38 (0.53) v. 2.46 (0.55); p=0.385 | - Did not account for: Race/Ethnicity, Physical activity; - More than half of the participants were born preterm;; - Data on twins is very likely to be correlated (unclear if this was acounted for); Funding: National Key Research and Development Program of China, National Natural Science Foundation of China, Chongqing Joint Program of Science and Health, Key Disciplines of Medical and Health Research of Yuhang District of Hangzhou City
Nguyen, 2020 ^10^; Netherlands; Generation R Study; Analytic N=3991; Participant characteristics: 50.7% Female; 67.4% Dutch; Higher maternal education: 63.1%; household income ≥2800 Euros/month: 69.5%; Selection: Enrolled participants at birth; Excluded those with missing FFQ or outcome data | Age at Dietary Pattern: 1 y; 8 y; [underlined: Diet Quality score (DQS]) [van der Velde, 2018]: Positive: Vegetables; Fruit; Nuts; Legumes; Whole grains; Dairy; Fish; Oils and fats; Negative: High-fat and processed meats; Sugar-containing beverages; Method(s):Index or Score Analysis | Age at Follow-up: 10y; DQS at 1 y; - FMI β: 0.02, 95% CI:−0.01, 0.05; - FFMI β: 0.03, 95% CI: −0.01, 0.06; - %BF β: 0.01, 95% CI: −0.02, 0.04; - BMI β: 0.05, 95% CI: 0.02, 0.07; - Wt β: 0.06, 95% CI: 0.03, 0.09; DQS at 8 y; - FMI β: −0.001, 95% CI: −0.03, 0.02; - FFMI β: 0.06, 95% CI: 0.04, 0.09; - %BF β: −0.02, 95% CI: −0.04, 0.01; - BMI β: 0.02, 95% CI: −0.003, 0.04; - Wt β: 0.04, 95% CI: 0.01, 0.06 | - Did not account for: Anthropometry at baseline (Excluding those with baseline Ob/OW yielded similar results); - Previously reported results with outcomes at age 6 y; Excluding children with baseline Ob/OWt yielded similar results; Excluding individual DQ components yielded similar results; Analyses of only Dutch children yielded similar results; Effect estimates; - DQ at 8 y & BMI or Wt results were generally significant in girls only when stratified; Funding: Erasmus Medical Center Erasmus University Rotterdam; the Netherlands Organization for Health Research and Development
Okubo, 2015 ^11^; United Kingdom; Southampton Women’s Survey; Analytic N=1018; Participant characteristics: 48% Female; 23.5% degree qualification or above; Race/ethnicity: NR; Selection: Excluded those with missing data. No body composition data at 6 y or dietary data for at least 2 ages | Age at Dietary Pattern: 6mo, 12mo; [underlined: ‘Infant guidelines’]: Positive: Vegetables; Potatoes and sweet potatoes; Cooked, dried and tinned fruit; Meat and fish; Fresh fruit; Beans and pulses; Pasta; Baby rice; Negative: Formula milk; Method(s):Factor/Cluster | Follow-up duration or age: 6y; Infant guidelines 6mo, T3 ref; - FM; ○ T1, β: 0.28, 95% CI: 0.05, 0.51; ○ T2, β: −0.02, 95% CI: −0.23, −0.19; ○ p=0.007; ○ per-unit, β: −0.13, 95% CI: −0.23, −0.04; - BMIz; ○ T1, β: 0.12, 95% CI: −0.10, 0.35; ○ T2, β: −0.05, 95% CI: −0.26, 0.16; ○ p=0.36; ○ per-unit, B: −0.04, 95% CI: −0.14, 0.05; Infant guidelines 12mo, T3 ref; - FM; ○ T1, β: 0.08, 95% CI: −0.16, 0.32; ○ T2, β: 0.2, 95% CI: −0.01, 0.42; ○ p=0.48; ○ per-unit, β: 0.04, 95% CI: −0.14, 0.07; - BMIz; ○ T1, β: −0.09, 95% CI: −0.31, 0.13; ○ T2, β: 0.2, 95% CI: −0.01, 0.40; ○ p=0.43; ○ per-unit, β: 0.04, 95% CI: −0.06, 0.14 | - Did not account for: Race and/or ethnicity; SEP (subgroup analyzed had higher education than primary cohort); Anthropometry (but no differences in GA, BW, maternal pre-BMI, maternal 25-OH-D); - Diet measured at 4 time points; Did not account for missing data; - Funding: Medical Research Council, the British Heart Foundation, Arthritis Research United Kingdom, the National Osteoporosis Society, the International Osteoporosis Foundation, the Cohen Trust, the National Institute for Health Research Southampton Biomedical Research
Olaya, 2013 ^12^; Columbia; Analytic N=76; Participant characteristics: 50% Female; Race and/or ethnicity NR; low-SEP; 53% of mothers completed HS; Selection: Enrolled infants who were participating in a growth-monitoring program from hospitals serving low-SEP families and exclusively breastfed at age 4mo | Age at Dietary Pattern: 6 to 12mo; [underlined: Intervention (NGG):] New guidelines group received individual, face-to-face nutrition counseling with 3 key messages: the importance of continuing BF alongside CF, red meat as a source of Fe to prevent anemia (>5 portions/wk, red meat, chicken liver and heart), and daily fruit and vegetables as part of a healthy diet (at 12mo, this group consumed more meat, red meat, fruit, vegetables, and legumes than Control); [underlined: Control (CG)]: Received standard complementary feeding advice from health care professionals (including meat consumption, but no advice on frequency or amount of foods was given) (at 12mo, this group was more likely to consume follow-on formula, milk, cow milk, and sweetened foods such as sugar, jelly, chocolate, sweets); Method(s): RCT | Age at Follow-up: 12mo; NGG vs. CG:; - MUACZ, at 12mo: −0.42, 95% CI: −0.84, 0.00; - ΔMUACZ, 6–12mo: 0.059, 95% CI: −0.26, 0.38; - WLZ at 12mo: −0.54, 95% CI: −0.96, −0.12; - ΔWLZ, 6–12mo: 0.09, 95% CI: −0.23, 0.42; - WAZ at 12mo: −0.46, 95% CI: −0.93, 0.00; - ΔWAZ 6–12mo: 0.18, 95% CI: −0.02, 0.39; - LAZ at 12mo: −0.98, 95% CI: −0.59, 0.39; - ΔLAZ 6–12mo: 0.13, 95% CI: −0.16, 0.43; - HCZ at 12mo: −0.15, 95% CI: −0.57, 0.28; - HCZ, 6–12mo: 0.11, 95% CI: −0.09, 0.31; - at 12mo, ~24% vs. 21% had LAZ < 2SD;; - at 6mo, 23.8% vs. 4.7% had LAZ < 2SD; p=0.02; No differences between groups at 12mo (mean or Δ 6–12mo) in MUACz, WAZ, LAZ, WLZ, or HCz | - Did not account for: N/A RCT (Education; Maternal age; Race/ethnicity; Feeding practices; Birth size; Gestational age); - Groups differed at baseline on key characteristics that were not adjusted for in analyses (father’s age, baseline weight, baseline MUAC);; - Control and intervention groups consumed similar CFB;; - Participants were not blinded; Cannot determine if outcome assessors or investigators were blinded;; - Larger-than-expected proportions of infants in both groups were consuming cow milk at age 6mo;; - Imbalances between groups in receipt of iron and vitamin A supplementation.; - Funding: Childhood Nutrition Research Centre; University College London Institute of Child Health; Pontificia Universidad Javeriana; Tommee Tippee
Robinson, 2009 ^13^; United Kingdom; Southampton Women’s Survey; Analytic N=536; Participant characteristics: 47% Female; Race/ethnicity NR; Selection: Singletons, who were followed-up from birth until age 4. | Age at Dietary Pattern: 12 mo; [underlined: Infant guidelines pattern:] High consumption of fruit, vegetables, cooked meat and fish, and other home-prepared foods (rice, pasta), and low consumption of commercial baby foods; Method(s): Factor/Cluster | Age at Follow-up: 4y; mean LM (kg); - < −0.68: 12.0, 95% CI: 11.7, 12.4; - −0.68 to 0: 12.3, 95% CI: 12.1, 12.6; - 0 to 0.68: 12.7, 95% CI: 12.4, 12.9; - ≥0.68: 12.6, 95% CI: 12.3, 12.9; - P-trend: 0.003; mean LMI (kg/m2); - <−0.68: 11.7, 95% CI: 11.5, 11.9; - −0.68 to 0: 11.8, 95% CI: 11.6, 11.9; - 0 to 0.68: 11.9, 95% CI: 11.8, 12.0; - ≥0.68: 11.9, 95% CI: 11.8, 12.1; - P-trend: 0.004; mean FM (kg); - <−0.68: 4.5, 95% CI: 4.3, 4.7; - −0.68 to 0: 4.7, 95% CI: 4.5, 4.9; - 0 to 0.68: 4.7, 95% CI: 4.5, 4.9; - ≥0.68: 4.5, 95% CI: 4.3, 4.6 P-trend: 0.781; mean FMI (kg); - <−0.68: 4.3, 95% CI: 4.1, 4.4; - −0.68 to 0: 4.3, 95% CI: 4.2, 4.5; - 0 to 0.68: 4.3, 95% CI: 4.2, 4.5; - ≥0.68: 4.1, 95% CI: 4.0, 4.3; - P-trend: 0.488; mean BMI (kg/m2); - <−0.68: 15.9, 95% CI: 15.6, 16.1; - −0.68 to 0: 16.1, 95% CI: 15.8, 16.3; - 0 to 0.68: 16.2, 95% CI: 16.0, 16.5; - ≥0.68: 16.1, 95% CI: 15.8, 16.3; P-trend: 0.102 | - Did not account for: Race/ethnicity (“Wide range of backgrounds”); Physical activity; - Cannot determine whether groups were similar at baseline on key characteristics;; - Cannot determine whether outcome assessors were blinded;; - Cannot determine the validity/reliability of some outcome measures (i.e., single vs multiple height, weight measures);; - Did not define age of introduction of CFB variable;; - Did not account for high loss to follow-up (55%); - Funding: Medical Research Council, University of Southampton, British Heart Foundation, Food Standards Agency
Rose, 2016 ^14^; United States; Infant Feeding Practices Study II (IFPS II); Analytic N=783; Participant characteristics: 51% Female; ~90% White; Middle income and most had at least some college education (>75%).; Selection: Participants with at least one response on FFQ at 9 mo were included. Participants with incomplete anthropometric data were excluded. Infants with birth weight >=5.331 kg were excluded. | Age at Dietary Pattern: 9mo; - [underlined: BFFV, Breastfed Fruits and Vegetables]: Breastmilk, fruits, and vegetables, and low intake of energy-dense foods; - [underlined: BFLV, Breastfed Low Variety]: Breastmilk, and low intake of fruits and vegetables, low diet variety; - [underlined: FFFV, Formula-Fed Fruits and Vegetables]: Formula, fruits, and vegetables, and low intake of energy-dense foods; - [underlined: FFLV, Formula-Fed Low Variety]: Formula, and low intake of fruits and vegetables, low diet variety; - [underlined: MXHED, Mixed High Energy Density]: Breastmilk and formula, low intake of fruits and vegetables, diet variety, and higher intake of energy-density foods (e.g. French fries, sweet foods); Method(s): Latent class analysis | Age at Follow-up: 1y; - MXHED had the highest prevalence of OW at 1y compared to all other classes. Both FFFV and FFLV had higher prevalence of OW at 1y relative to both BF classes (BFFV, BFLV). (Values NR).; WLZ, LS means; - BFFV: 0.09; - BFLV: −0.02; - FFFV: 0.47; - FFLV: 0.70; - MXHED: 0.74; - P-value: <0.01; - FFLV, MXHED had highest WLZ.; WAZ, LS means; - BFFV: −0.30; - BFLV: −0.60; - FFFV: −0.06; - FFLV: −0.11; - MXHED: −0.10; - P-value: <0.0001; - FFFV had highest WAZ. | - Did not account for: Physical activity; - Outcome assessors were not blinded (maternal report);; - Did not use valid/reliable methods to measure outcomes (weight was self-reported by mothers);; - Did not account for high loss to follow-up (43%)’;; - Did not describe p-values for all analyses reported; - Funding: USDA
Santos, 2019 ^15^; Brazil; Pelotas Birth Cohort Study; Analytic N=3374; Participant characteristics: 48% Female; 15.1% =<4 y of formal education; Children’s skin color (white): 71.4%; Selection: Excluded those missing BMI at 6 y or LFU | Age at Dietary Pattern: 1y, 2y; [underlined: ‘Milks’:] positive for breast milk, negative for cow’s milk; [underlined: ‘Staple’]: positive for rice and beans, negative for pasta; [underlined: ‘Beverages’]: positive for juice, negative for water and tea; [underlined: ‘Snacks’]: positive for coffee, bread, cookies, negative for fruits (1y) or yogurt (2y); [underlined: ‘Meat and vegetables’]: positive for meats, vegetables, legumes, potato and cassava, and fruits; Method(s):Factor/Cluster | Age at Follow-up: 6y; T1, β=1, ref; Milks, 1 y &; - Trunk FM % z, p-trend = 0.084; ○ T2, β= −0.06, 95% CI: −0.15, 0.03; ○ T3, β= −0.08, 95% CI: −0.18, 0.02; - Gynoid FM % z, p-trend = 0.001; ○ T2, β= 0.06, 95% CI: −0.03, 0.14; ○ T3, β= 0.16, 95% CI: 0.06, 0.27; - BMIz at 6y, p-trend = 0.205; ○ T2,β= 0.00, 95% CI: −0.13, 0.12; ○ T3, β= −0.10, 95% CI: −0.23, 0.04; Staple, 1y; - Trunk FM % z; ○ T2, β= −0.09, 95% CI: −0.18, 0.00; ○ T3, β= −0.06, 95% CI: −0.15, 0.03; ○ p-trend = 0.168; - Gynoid FM % z; ○ T2, β= 0.07, 95% CI: −0.01, 0.16; ○ T3, β= 0.04, 95% CI: −0.05, 0.13, p= p-trend = 0.340; - BMIz; ○ T2, β= −0.10, 95% CI: −0.22, 0.03; ○ T3, β= −0.02, 95% CI: −0.15, 0.10; ○ p-trend = 0.733; Meat and vegetables, 1y; - Trunk FM % z; ○ T2, β= 0.01, 95% CI: −0.08, 0.09; ○ T3, β= −0.00, 95% CI: −0.09, 0.09; ○ p-trend = 0.962; - Gynoid FM % z; ○ T2, β= 0.01, 95% CI: −0.08, 0.09; ○ T3, β= −0.03, 95% CI: −0.12, 0.06; ○ p-trend = 0.559; - BMIz; ○ T2, β= 0.04, 95% CI: −0.09, 0.16; ○ T3, β= 0.07, 95% CI: −0.06, 0.20; ○ p-trend = 0.292; Beverages, 1y; - Trunk FM % z; ○ T2, β= 0.06, 95% CI: −0.03, 0.15; ○ T3, β= −0.01, 95% CI: −0.01, 0.16; ○ p-trend = 0.088; - Gynoid FM % z; ○ T2, β= −0.03, 95% CI: −0.11, 0.06; ○ T3, β= −0.06, 95% CI: −0.15, 0.03; ○ p-trend = 0.179; - BMIz; ○ T2, β= 0.01, 95% CI: −0.11, 0.13; ○ T3, β= 0.06, 95% CI: −0.06, 0.19; ○ p-trend = 0.332; Snacks, 1y; - Gynoid FM % z; ○ T2, β= −0.01, 95% CI: −0.10, 0.08; ○ T3, β= 0.07, 95% CI: −0.02, 0.15; ○ p-trend = 0.138; - Trunk FM % z; ○ T2, β= −0.04, 95% CI: −0.12, 0.05; ○ T3, β= −0.06, 95% CI: −0.15, 0.02; ○ p-trend = 0.158; - BMIz; ○ T2, β= −0.01, 95% CI: −0.14, 0.11; ○ T3, β= −0.10, 95% CI: −0.23, 0.02; ○ p-trend = 0.112; Milks, 2y; - Trunk FM % z; ○ T2, β= −0.02, 95% CI: −0.11, 0.07; ○ T3, β= −0.01, 95% CI: −0.11, 0.10; ○ p-trend = 0.883; - Gynoid FM % z; ○ T2, β= 0.00, 95% CI: −0.09, 0.09; ○ T3, β= −0.04, 95% CI: −0.14, 0.06; ○ p-trend = 0.512; - BMIz; ○ T2, β= −0.03, 95% CI: −0.16, 0.09; ○ T3, β= 0.06, 95% CI: −0.08, 0.21; ○ p-trend = 0.451; Staple, 2y; - Trunk FM % z; ○ T1, β=1, ref; ○ T2, β= 0.07, 95% CI: −0.02, 0.16; ○ T3, β= 0.10, 95% CI: 0.01, 0.19; ○ p-trend = 0.027; - Gynoid FM % z; ○ T2, β= −0.08, 95% CI: −0.17, 0.01; ○ T3, β= −0.11, 95% CI: −0.20, −0.02; ○ p-trend = 0.020; - BMIz; ○ T2, β= 0.09, 95% CI: −0.04, 0.22; ○ T3, β= 0.11, 95% CI: −0.02, 0.24; ○ p-trend = 0.085; Meat and vegetables, 2y; - Trunk FM % z; ○ T2, β= 0.03, 95% CI: −0.06, 0.12; ○ T3, β= 0.01, 95% CI: −0.08, 0.10; ○ p-trend = 0.868; - Gynoid FM % z; ○ T2, β= −0.05, 95% CI: −0.14, 0.04; ○ T3, β= −0.02, 95% CI: −0.11, 0.07; ○ p-trend = 0.708; - BMIz; ○ T2, β= 0.03, 95% CI: −0.10, 0.15; ○ T3, β= 0.07, 95% CI: −0.06, 0.20; ○ p-trend = 0.271; Beverages, 2y; - Trunk FM % z; ○ T2, β= −0.02, 95% CI: −0.11, 0.07; ○ T3, β= 0.04, 95% CI: −0.05, 0.13; ○ p-trend = 0.372; - Gynoid FM % z; ○ T2, β= 0.02, 95% CI: −0.07, 0.11; ○ T3, β= −0.01, 95% CI: −0.10, 0.08; ○ p-trend = 0.890; - BMIz; ○ T2, β= −0.03, 95% CI: −0.16, 0.09; ○ T3, β= −0.07, 95% CI: −0.19, 0.06; ○ p-trend = 0.306; Snacks, 2y; - Trunk FM % z; ○ T2, β= −0.06, 95% CI: −0.15, 0.04; ○ T3, β= −0.05, 95% CI: −0.14, 0.05; ○ p-trend = 0.310; - Gynoid FM % z; ○ T2, β= 0.05, 95% CI: −0.04, 0.14; ○ T3, β= 0.09, 95% CI: 0.00, 0.18; ○ p-trend = 0.053; - BMIz; ○ T2, β= −0.11, 95% CI: −0.24, 0.02; ○ T3, β= −0.08, 95% CI: −0.22, 0.05; ○ p-trend = 0.223 | - Did not account for: Race/Ethnicity (*skin color), Physical activity; - Corpulence data also reported (a composite of body circumference (waist, hip, seat, chest, abdomen, knee, calf, and biceps circumferences), diameters (sagittal diameter, waist, abdomen width), and volumes (body volume and torso); - Funding: Wellcome Trust, WHO, Brazilian National Research Council, Brazilian Ministry of Health, ‘Science without Borders’ Brazilian scheme
Vadiveloo, 2019 ^16^; United States; Nurture Cohort; Analytic N=449; Participant characteristics: SEP: 65.2% NHB; 59.3% low income (<20,000/y); 18.9% mothers <high school education; Selection: Recruited mothers between 20 and 36 weeks’ gestation; Excluded mothers <18 y; mothers without singleton pregnancy; without intention to remain in study area for at least 12 months; with missing dietary or outcome data | Age at Dietary Pattern: 4 to 12 mo; [underlined: HFS]: Positive: Vegetables (no fried potatoes); Fruit (no 100% fruit juice); [underlined: UnFS]: Positive: French Fries; Ice cream; Baby Snacks; Sweets; Healthiest (10 points) = ≥ 2 servings/d of foods in HFS AND ≤ 1 serving/d of foods in UnFS; Moderately healthy(0 points) = ≥ 2 servings/d of foods in HFS And ≤ 1 serving/d of foods in UnFS; Moderately unhealthy (−10 points)= > 2 servings/d of foods in HfS And > 1 serving/d of foods in UnFS; Unhealthy (ref) (−20 points)= < 2 servings/d of foods included in HFS AND > 1 serving/d of foods included in UnFS; Method(s): Index or Score Analysis | Age at Follow-up: 12mo; WFL z-score, mean [SE]; - HFS: Q1, 0.56 [0.09]; Q2, 0.64 [0.10]; Q3, 0.66 [0.09]; Q4, 0.73 [0.10]; p-trend=0.65; - UnHFS: Q1, 0.42 [0.09]; Q2, 0.63 [0.09]; Q3, 0.79 [0.09]; Q4, 0.75 [0.09]; p-trend=0.02; - Moderately unhealthy v. Unhealthy: 0.06, 95% CI: −0.17, −0.29; - Moderately healthy v. Unhealthy: −0.33, 95% CI: −0.63, −0.03, p<0.05; - Healthiest v. Unhealthy: 0.02, 95% CI: −0.30, 0.33 | - Did not account for: Physical Activity, SEP, Race and/or ethnicity (~66% Non-Hispanic, Black); - Diet assessed at 3 time points (ages 6, 9, and 12mo) with HFS and UnHFS scores based on mean value from between age 4 and 12 mo.; - Did not report how missing data were handled or how analytic sample size was determined; - Funding: NIH/NIDDK
Voortman, 2016 ^17^; Netherlands; Generation R Study; Analytic N=2026; Participant characteristics: 50.5% Girls; Higher education: 71.0%; Net household income ≥2200 Euro: 79.7%; Selection: NR | Age at Dietary Pattern:1 y; [underlined: Diet Quality Score (DQS]), Positive: Vegetables; Fruit; Nuts; Legumes; Whole grains; Dairy; Fish; Oils and fats; Negative: High-fat and processed meats; Sugar-containing beverages; [underlined: Health conscious]: Vegetables; Pasta and rice; Potatoes; Vegetable oils; Legumes; Fruit; Fish; Meat; [underlined: Western-like]: Confections; Savory snacks; Sugar-containing beverages; Other fats; Refined cereals; Meat; Soups and sauces; [underlined: RRR Pattern 1]: Soups and sauces; Fish; Vegetables; Potatoes; Meat; Sugar-containing beverages; [underlined: RRR Pattern 2]: Pasta and Rice; Whole cereals; Vegetables; Vegetable oils; Fruit; Non-sugar containing beverages; Dairy; Other fats; Method(s): Index, Factor/Cluster, RRR | Age at Follow-up: 6y; FMI (Q1 ref); - DQS, per SD, β: 0.01, 95% CI: −0.02, 0.04; ○ Q2: 0.03, 95% CI: −0.06, 0.11; ○ Q3: −0.01, 95% CI: −0.09, 0.08; ○ Q4: 0.07, 95% CI: −0.01, 0.16; - ‘Health-conscious’, per SD, β: 0.00, 95% CI: −0.03, 0.03; ○ Q2: 0.02, 95% CI: −0.07, 0.10; ○ Q3: 0.03, 95% CI: −0.05, 0.12; ○ Q4: 0.04, 95% CI: −0.05, 0.13; - Western-like, per SD, β: −0.01, 95% CI: −0.04, 0.03; ○ Q2: 0.02, 95% CI: −0.06, 0.11; ○ Q3: 0.06, 95% CI: −0.03, 0.15; ○ Q4: −0.01, 95% CI: −0.11, 0.09; - RRR pattern 1, per SD, β: 0.09, 95% CI: 0.06, 0.13; ○ Q2: 0.10, 95% CI: 0.01, 0.18; ○ Q3: 0.09, 95% CI: 0.01, 0.18; ○ Q4: 0.18, 95% CI: 0.10, 0.27; - RRR pattern 2, per SD, β: −0.04, 95% CI: −0.07, 0.01; ○ Q2: −0.06, 95% CI: −0.15, 0.02; ○ Q3: −0.01, 95% CI: −0.10, 0.08; ○ Q4: −0.07, 95% CI: −0.17, 0.03; FFMI (Q1 ref); - DQS per SD β: 0.05, 95% CI: 0.01, 0.08; ○ Q2: 0.09, 95% CI: −0.02, 0.20; ○ Q3: 0.14, 95% CI: 0.02, 0.25; ○ Q4: 0.19, 95% CI: 0.08, 0.30; - Health-conscious, per SD β: 0.04, 95% CI: 0.00, 0.08; ○ Q2: 0.02, 95% CI: −0.09, 0.13; ○ Q3: 0.13, 95% CI: 0.02, 0.24; ○ Q4: 0.17, 95% CI: 0.06, 0.29; - Western-like, per SD β: 0.02, 95% CI: −0.03, 0.07; ○ Q2: −0.01, 95% CI: −0.12, 0.10; ○ Q3: 0.15, 95% CI: 0.04, 0.27; ○ Q4: 0.09, 95% CI: −0.04, 0.22; - RRR pattern 1 per SD β: 0.08, 95% CI: 0.03, 0.12; ○ Q2: 0.08, 95% CI: −0.03, 0.19; ○ Q3: 0.07, 95% CI: −0.04, 0.18; ○ Q4: 0.23, 95% CI: 0.11, 0.35; - RRR pattern 2, per SD β: 0.06, 95% CI: 0.01, 0.10; ○ Q2: −0.02, 95% CI: −0.13, 0.10; ○ Q3: 0.18, 95% CI: 0.06, 0.29; ○ Q4: 0.19, 95% CI: 0.06, 0.32; BF% (Q1 ref); - Diet quality score, per SD β: 0.00, 95% CI: −0.03, 0.03; ○ Q2: 0.01, 95% CI: −0.08, 0.10; ○ Q3: −0.05, 95% CI: −0.14, 0.04; ○ Q4: 0.02, 95% CI: −0.08, 0.11; - Health-conscious, per SD β: −0.01, 95% CI: −0.04, 0.03; ○ Q2: 0.01, 95% CI: −0.09, 0.10; ○ Q3: −0.01, 95% CI: −0.11, 0.08; ○ Q4: −0.01, 95% CI: −0.11, 0.08; - Western-like, per SD β: −0.01, 95% CI: −0.05, 0.04; ○ Q2: 0.05, 95% CI: −0.05, 0.14; ○ Q3: 0.03, 95% CI: −0.07, 0.13; ○ Q4: −0.02, 95% CI: −0.13, 0.09; - RRR pattern 1 per SD β: 0.08, 95% CI: 0.04, 0.12; ○ Q2: 0.10, 95% CI: 0.01, 0.19; ○ Q3: 0.08, 95% CI: −0.01, 0.18; ○ Q4: 0.14, 95% CI: 0.04, 0.24; - RRR pattern 2 per SD β: −0.05, 95% CI: −0.09, −0.01; ○ Q2: −0.07, 95% CI: −0.16, 0.03; ○ Q3: −0.06, 95% CI: −0.16, 0.04; ○ Q4: −0.12, 95% CI: −0.23, −0.02; BMI (Q1 ref); - DQS, per SD: 0.04, 95% CI: 0.01, 0.07; ○ Q2: 0.07, 95% CI: −0.02, 0.16; ○ Q3: 0.07, 95% CI: −0.02, 0.16; ○ Q4: 0.18, 95% CI: 0.08, 0.27; - Health-conscious, per SD: 0.03, 95% CI: −0.00, 0.07; ○ Q2: 0.03, 95% CI: −0.07, 0.12; ○ Q3: 0.10, 95% CI: 0.01, 0.19; ○ Q4: 0.14, 95% CI: 0.05, 0.24; - Western-like, per SD: 0.01, 95% CI: −0.03, 0.05; ○ Q2: 0.02, 95% CI: −0.07, 0.11; ○ Q3: 0.12, 95% CI: 0.02, 0.21; ○ Q4: 0.04, 95% CI: −0.07, 0.14; - RRR pattern 1, per SD: 0.10, 95% CI: 0.06, 0.14; ○ Q2: 0.12, 95% CI: 0.03, 0.21; ○ Q3: 0.12, 95% CI: 0.03, 0.21; ○ Q4: 0.25, 95% CI: 0.16, 0.35; - RRR pattern 2, per SD: 0.01, 95% CI: −0.03, 0.04; ○ Q2: −0.06, 95% CI: −0.15, 0.03; ○ Q3: 0.07, 95% CI: −0.03, 0.16; ○ Q4: 0.06, 95% CI: −0.04, 0.17; Weight (Q1 ref); - DQS per SD β: 0.06, 95% CI: 0.03, 0.10; ○ Q2: 0.04, 95%CI: −0.05, 0.13; ○ Q3: 0.04, 95% CI: −0.05, 0.14; ○ Q4: 0.19, 95% CI: 0.10, 0.29; - Health conscious, per SD β: 0.03, 95% CI: −0.01, 0.07; ○ Q2: 0.04, 95% CI: −0.06, 0.13; ○ Q3: 0.12, 95% CI: 0.02, 0.21; ○ Q4: 0.13, 95% CI: 0.03, 0.23; - Western-like per SD β: 0.00, 95% CI: −0.04, 0.04; ○ Q2: −0.01, 95% CI: −0.11, 0.08; ○ Q3: 0.11, 95% CI: 0.01, 0.20; ○ Q4: 0.03, 95% CI: −0.08, 0.14; - RRR Pattern 1, per SD β: 0.10, 95% CI: 0.06, 0.14; ○ Q2: 0.09, 95% CI: 0.00, 0.19; ○ Q3: 0.14, 95% CI: 0.05, 0.24; ○ Q4: 0.23, 95% CI: 0.13, 0.33; - RRR Pattern 2, per SD β: 0.02, 95% CI: −0.02, 0.06; ○ Q2: −0.06, 95% CI: −0.15, 0.04; ○ Q3: 0.11, 95% CI: 0.01, 0.21; ○ Q4: 0.04, 95% CI: −0.07, 0.15; Height (Q1 ref); - DQS, per SD β: 0.05, 95% CI: 0.01, 0.09; ○ Q2: −0.01, 95% CI: −0.13, 0.10; ○ Q3: −0.02, 95% CI: −0.14, 0.09; ○ Q4: 0.15, 95% CI: 0.03, 0.27; - Health conscious, per SD β: 0.01, 95% CI: −0.04, 0.05; ○ Q2: 0.05, 95% CI: −0.07, 0.16; ○ Q3: 0.11, 95% CI: −0.01, 0.22; ○ Q4: 0.08, 95% CI: −0.04, 0.20; - Western-like, per SD β: 0.00, 95% CI: −0.05, 0.05; ○ Q2: −0.05, 95% CI: −0.16, 0.07; ○ Q3: 0.04, 95% CI: −0.07, 0.16; ○ Q4: 0.02, 95% CI: −0.11, 0.15; - RRR pattern 1, per SD β: 0.05, 95% CI: 0.00, 0.10; ○ Q2: 0.04, 95% CI: −0.08, 0.15; ○ Q3: 0.12, 95% CI: 0.00, 0.24; ○ Q4: 0.13, 95% CI: 0.01, 0.25; - RRR pattern 2 per SD β: 0.02, 95% CI: −0.03, 0.07; ○ Q2: −0.03, 95% CI: −0.15, 0.09; ○ Q3: 0.13, 95% CI: 0.01, 0.25; ○ Q4: 0.01, 95% CI: −0.12, 0.15 | - Did not account for: Baseline BMI (at 1 y) was adjusted in some, but not all models; - The paper does not present a model with adjusted BMI at 1 y, especially for categorical measurement (quartiles).; - Multiple analysis (index, factor/cluster and RRR) were conducted without adjusting for p-value. P-trend not provided.; - Single time point measurement of the exposure; - Funding: Erasmus Medical Center Erasmus University Rotterdam; the Netherlands Organization for Health Research and Development
Wen, 2014a ^18^; United States; Infant Feeding Practices Study II (IFPS II); Analytic N=530; Participant characteristics: 50% female; 91% White, 1% African American, 3% Hispanic, 3% Asian/Pacific Islander; 40.6% income >$60K; Selection: Full-term newborns (gestational age ≥37 wks) with complete data on gender. Participants with complete data on infant growth outcomes at both 6 and 12 mo. | Age at Dietary Pattern: 6 mo; Four dietary patterns were identified using principal component analysis, and infants were assigned an adherence score to each pattern at 6mo:; - Infant guideline solids: Baby cereal, fruit, vegetables, meat/chicken; - High sugar/fat/protein: Sweet drinks, French fries, fish/shellfish, nut foods, eggs, sweet foods; - High dairy/regular cereal: Cow’s milk, other dairy, 100% juice, non-baby cereals/starches; - Formula: Formula and low intakes of breast milk; Method(s):Factor/Cluster | Age at Follow-up: Δ 6 –2mo; BMIz, β, 95% CI; - High sugar/fat/protein: 1.00, 95% CI: 0.11, 1.89, p<0.05; - Formula: 0.25, 95% CI: 0.09, 0.40, p<0.05; - High dairy/regular cereal: 0.32, 95% CI: 0.10, 0.53, p<0.05; - Infant guideline solids: 0.06, 95% CI: −0.09, 0.22, NS; Δ LAZ, β, 95% CI; - High sugar/fat/protein: −1.36, 95% CI: −2.35, −0.37, p <0.05; - Formula: 0.01, 95% CI: 0.01, 95% CI: −0.16, 0.18, NS; - High dairy/regular cereal:, 95% CI: 0.10, 0.53, p<0.05; Infant guideline solids: 0.12, 95% CI: −0.05, 0.29, NS | - Did not account for: Physical activity; Birth size (although accounted for growth at 6mo); - Dietary pattern adherence was associated with birth weight, which was not adjusted for in analyses;; - Outcome assessors were not blinded (maternal report);; - Did not use valid/reliable measures to assess outcomes (maternal report of infant weight, length);; - Did not account for high loss to follow-up (85%); - Funding: Food and Drug Administration, Centers for Disease Control and Prevention

a Abbreviations: BF, Body fat (total unless specified as trunk, gynoid, android, etc.); BF%, Body fat percentage; DM, Diabetes (T1 a/o T2); FFM, Fat-free mass; FFMI, Fat-free mass index; FM, Fat mass (total, unless specified as trunk, gynoid, android, etc.); FMI, Fat mass index; F/U, Follow-up; GDM, gestational diabetes mellitus; HC, head circumference; HipC, hip circumference; HS, high school; HTN, hypertension; Hx, History; ITT, intent-to-treat; N/A, Not applicable; NHLBI, National Heart, Lung, and Blood Institute; NIDDK, National Institute of Digestive Kidney; NIFA, National Institute of Food and Agriculture; NIH, National Institutes of Health; NR, not reported; NS, not statistically significant Ob, Obesity; OW, Overweight; PA, Physical activity; PP, per-protocol SEP/SES, Socioeconomic position/status; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, Treatment; USDA, United States Department of Agriculture; WC, waist circumference; WHO, World Health Organization; WHR, waist-hip ratio; Wt, Body weight

Table 7 Risk of bias for randomized controlled trials examining dietary patterns consumed from birth up to 24 months of age and growth, body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Olaya, 2013 ^12^ | Low | Low | Some concerns | Low | Low | Some concerns | Some concerns

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (August 2019 version)” Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531 )

Table 8 Risk of bias for observational studies examining dietary patterns consumed from birth to age 24 months and growth, body composition and risk of obesity^*^ * Possible ratings of low, moderate, serious, critical, or no information determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool (ROBINS-E Development Group ( Higgins J, Morgan R, Rooney A, Taylor K, Thayer K, Silva R, Lemeris C, Akl A, Arroyave W, Bateson T, Berkman N, Demers P, Forastiere F, Glenn B, Hróbjartsson A, Kirrane E, LaKind J, Luben T, Lunn R, McAleenan A, McGuinness L, Meerpohl J, Mehta S, Nachman R, Obbagy J, O'Connor A, Radke E, Savović J, Schubauer-Berigan M, Schwingl P, Schunemann H, Shea B, Steenland K, Stewart T, Straif K, Tilling K, Verbeek V, Vermeulen R, Viswanathan M, Zahm S, Sterne J). Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

Article | Confounding | Exposure classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Abraham, 2012 ^1^ | High | Some concerns | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Agnihotri, 2021^2^ | High | Low | Low | Low | High | Low | Low | High
Amaro-Rivera, 2019^3^ | High | Low | Low | Low | High | Some concerns | Some concerns | High
Au, 2023^4^ | Some concerns | Low | Low | Low | Low | Low | Low | Some concerns
Baird, 2008 ^5^ | High | Low | Low | Low | Some concerns | Some concerns | Some concerns | High
Bell, 2013 ^6^ | High | Low | Low | Low | Some concerns | Some concerns | Low | High
Golley, 2013^7^ | Some concerns | Some concerns | Low | Low | High | Some concerns | Some concerns | High
Hohman, 2017^8^ | High | Low | Low | Some concerns | Low | Some concerns | Low | High
Jin, 2022^9^ | Some concerns | Low | Low | Low | Some concerns | Some concerns | Some concerns | High
Nguyen, 2020^0^ | Some concerns | Low | Low | Low | Low | Low | High | High
Okubo, 2015^1^ | High | Low | Low | Low | Some concerns | Low | Some concerns | High
Robinson, 2009 ^3^ | High | Low | Low | Low | High | Low | Some concerns | High
Rose, 2016^4^ | Some concerns | Some concerns | Low | Low | High | High | Some concerns | High
Santos, 2019^5^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Vadiveloo, 2019^6^ | High | Low | Low | Low | High | Some concerns | Some concerns | High
Voortman, 2016^7^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns | High
Wen, 2014^8^ | High | Some concerns | Low | Low | High | High | Some concerns | High

## Children and adolescents

Sixty-two articles met inclusion criteria that examined the relationship between dietary patterns consumed by children and adolescents and growth, body composition, and risk of obesity.^2,10,11,15,19–76^ The included articles were published between January 2000 and May 2023 and came from 3 randomized controlled trials^24^, ^49^, ^59^ and 59 prospective cohort studies (Table 10).

### Description of the evidence

#### Population

Sample sizes ranged from N=64 to N=104 in the intervention studies and from N=39 to N=27,406 in the observational studies. Studies included participants who were at risk of chronic disease or exclusively those with overweight/obesity or metabolic syndrome. ^21,22,24,27,36,41,43,45,47,49,50,53,58,59^ Studies enrolled participants regardless of sex (i.e., both boys and girls in relatively equal amounts), except one intervention exclusively enrolled female adolescents.^24^

Many of the articles reported some information on the socioeconomic position (SEP) of participants, but the type of characteristics varied widely across studies. Across 38 articles, the most common characteristics were parental education ^2,15,19,21,22,26,48,51,60,63,66–68,70,72,73^socioeconomic status (SES)^15,22,28,31,42,43,46,56,61,75^, household income or assets.^10,19,26,32,46,49,66,70^ One article reported food security/WIC/SNAP status of participants.^45^ Most studies included participants from a wide range of SEP or with SES representative of the regional population, and two studies exclusively enrolled children and adolescents in households with lower-income and/or from SE-disadvantaged schools.^19,53^

Only 8 studies reported information on the race and/or ethnicity of participants and there was considerable variation, including “African American/Black”, “Mexican-heritage”, “Non-white”, “Other/mixed race”, “Spanish-heritage”, and “White skin colour”. Ethnicity of participants was reported as Hispanic or Non-Hispanic in 3 articles^26,45,70^ and primarily Samoan ethnicity in 1 article.^32^ Many articles included information on the heritage of participants and/or country of birth e.g., “indigenous Australian”, “Brazilian”, “Iranian”, “Norwegian”, “Portuguese”. Studies were conducted in the following countries: Australia ^30,43^; Brazil ^15,22^France ^63^; Germany ^72^; Greece ^59^; Iran ^24^; Japan ^65^; Mexico ^19^; Norway ^2,69^; Portugal ^36,39,40,52,60,73,74^; Samoa ^32^; South Korea ^49^; Spain ^21,56^; The Netherlands^10,48,61,66,67,75^; United Kingdom ^11,20,28,29,31,68^; United States ^26,45,46,54,70^; and multiple countries: Germany, Belgium, Italy, Poland, and Spain ^51^; and Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, and Spain.^42,58,71^

A single cohort contributed multiple included articles, but represented unique data on dietary patterns, outcomes, and/or participants as follows: 2 articles from the Amsterdam Born Children and their Development (ABCD) study; 5 articles from the Avon Longitudinal Study of Parents and Children (ALSPAC) cohort; 2 articles from the GECKO Drenthe birth cohort; 2 articles from Generation R Study; 5 articles from Generation XXI study; 3 articles from the Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS (IDEFICS) study; and 2 articles from the Norwegian Mother, Father and Child (MoBa) cohort study.

#### Intervention/exposure and comparator

Dietary patterns were assessed in participants ranging in age from 2 up to 18 years. Dietary intake was assessed using a variety of measures across studies, including validated food frequency questionnaire, 24-hour recalls, and food diaries. Diet assessments were conducted at more than one time point with repeated measures in 40 articles or only once/at baseline in 15 articles. Analytic approaches to examine/derive dietary patterns included:

- Investigator-assigned dietary intervention ^21,24,59^
- A priori index or score derivation^2,10,19,26,28,30,43,46,48,49,54,56,65–67,69,71–73,75^
- A posteriori factor, cluster, or latent class analysis^11,15,22,29,32,51,60,61^ ^39,40,42,43,52,58,63,67,68^
- Reduced rank regression^20^

Labels (names) of dietary patterns widely varied across the body of evidence and examples include “Traditional”, “Core”, “Healthier”, “Healthy”, “Snacking”, “Mediterranean”, “Western”, “Unhealthy”, “Treats”, “Sweet”, “Full-fat”, “Energy-dense foods”, “Processed”, and “Ultra-processed food (UPF)”. A visualization of all dietary pattern components in each dietary pattern examined in relation to outcomes of interest is available in Appendix 6: Dietary pattern visualization

#### Outcomes

Most studies measured weight, height, and body composition using standard methods (i.e., duplicate/triplicate and calibrated scales) and few studies obtained by self- or parent-reported weight and height. Across the body of evidence, the following outcomes were reported:

- Growth
  ○ Weight change or gain^10,24,31,32,46,49,61,72^
  ○ Height change^10,32,49,65^
- Body Composition
  ○ Total fat-mass (FM), FM index (FMI), or % FM ^10,11,15,20,21,28,31,39,40,42,49,66,68,71,72^,
  ○ Lean mass (LM) or LM index (LMI), or fat-free mass (FFM) or FFM index (FFMI)^10,31,42,68,72^
  ○ Hepatic fat ^21^
  ○ Excess adiposity^20^
  ○ Adiposity rebound^63^
  ○ Waist circumference (WC)/abdominal obesity^15,19,21,24,28,30,31,39,40,42,48,52,56,71,72^
  ○ BMI^10,11,15,22–28,30–43,45–51,54,55,58–60,62,64,65,70,72–76^
- Risk of obesity/overweight, obesity, overweight, and/or high BMI ^2,29,39,40,48,56,58,67,69,75^

### Synthesis of the evidence

Table 10 describes all included studies. The evidence synthesis focused on the studies with fewer limitations, which included studies that a) conducted repeated dietary assessments during follow-up compared to those that only assessed diet once/at baseline, b) controlled for baseline anthropometry compared to those that did not, c) objectively measured outcomes of interest (e.g., weight, height) compared to using self- or parent-report, and d) were designed to directly compare the exposures and outcomes of interest compared to those designed for other purposes. However, similar themes across the entire body of evidence were found among the studies with fewer limitations.^11,15,22,27,31,32,36,38,42,43,46–48,50,51,55,57,60,64,69,73,76^

Lower risk of obesity/overweight ^69^, fat mass ^11,46,64^, BMI or reduced-gain in BMI ^46,48,64^, smaller waist circumference/central fat-mass ^48,64^, and lower odds of excess weight/weight gain^46^ were associated with dietary patterns consumed at ages ranging from 3 up to 15 years. All of these dietary patterns were examined using index/score analysis and scored components similarly as follows: positive (representing higher intakes from) vegetables, fruit, nuts, whole grains, fish/seafood, dairy; and negative (representing lower intakes from) red and processed meats, sugar-sweetened foods and drinks, and salty snacks (sodium).

- These specific dietary patterns tended to reflect higher diet quality with overall more nutrient-dense components and fewer energy-dense components.
- Additional components varied between dietary patterns, such as fish and seafood either scored separately or combined with other components such as meat or protein foods. The level of specificity in components also varied, such as positively scoring “dairy/dairy products” collectively or only low-fat and unsweetened dairy specifically.
- Some articles reported consistently significant results across multiple time points and/or outcomes at follow-up. For example, Hu et al.^46^ reported that baseline and increased a Priori Diet Quality Scores (APDQS) were associated with significantly lower BMI and reduced excess weight gain over the first five years of follow-up, the last five years of follow-up, as well as across the overall 10-year follow-up range, ~ ages 15 to 25 years.
- Not all of the reported results in these studies reached statistical significance. For example, Okubo et al.^11^ reported that dietary pattern scores at age 3 years reflecting higher intakes of fish and shellfish, vegetables (salad, green, root, other), and fruits were significantly associated with lower fat-mass but were not significantly associated with lower BMI or risk of obesity/overweight at age 6 years. While Krijger et al ^48^ reported both DASH scores and children’s Diet Quality scores were significantly associated with lower BMI, only DASH scores were additionally associated with significantly lower waist circumference, and neither score was associated with overweight/obesity at age 11–12 years.

Higher risk of obesity/overweight^47,76^, and/or higher BMI^22,31,32,38,51,60,73^, fat mass^31,38,47^,, body weight, and/or larger waist circumference or waist-hip ratio^31,42,76^ between ages ranging from 4 to 6 years up to 24 years old were associated with dietary pattern consumption at ages 2 up to 14 years. Many of these dietary patterns were derived from data-driven methods except for five articles that examined dietary patterns with scores based on consumption of foods classified as “ultra-processed” by the Nova food classification system. The characteristics in common across these dietary patterns included higher intakes of potatoes and fried potatoes, refined grains, meats (red and processed and/or others), dairy (particularly whole fat/sweetened), sugar-sweetened drinks, saturated fats (i.e., butter, margarines, and/or spreads), sugar-sweetened and/or salty/savory snack foods and lower intakes of vegetables, fruit, whole or “high-fiber” grains. However, there were additional components that varied between dietary patterns, such as chocolate, biscuits, and fried/scrambled eggs.

- These specific dietary patterns tended to reflect poorer diet quality with overall fewer nutrient-dense components and more energy-dense components.
- Among these studies, many additional results were reported that did not reach statistical significance. For example, Luque et al.^51^ reported significantly higher BMI at age 8 years among those consuming a ‘Core Foods’ dietary pattern at age 2 years that reflected higher intakes of fruit, vegetables, potatoes, fish, white and red meat, and olive oil, but no significant associations were found between either consumption of the ”Poor-Quality Fats and Sugars’ (characterized by potatoes, soft cheese, saturated spreads, fruit juices, and teas and lower intakes of fish and olive oil) or ‘Protein Sources’ dietary patterns (higher in vegetables, potatoes, white meat, red meat, processed fish, eggs, chips and snacks, flavored milk) and BMI.
- In another example, Choy, et al.^32^ reported significantly higher BMI among those consistently consuming a ‘Modern’ dietary pattern at ages 2 to 4 years, no statistically significant associations were found between that dietary pattern and changes in weight or height, nor for a ‘Neotraditional’ dietary pattern and BMI, weight or height at follow-up 2 years later.
- Fernandez-Alvira et al.^42^ reported that consistent “Processed” dietary pattern consumption (from baseline age ~2 to 9 years through follow-up 2 years later) or changing from “Processed” to a “Sweet” dietary pattern at follow-up was significantly associated with higher FMI-z, BMIz, and waist-circumference z-score (WC-z) gain. Consumption of either a “Processed” or “Sweet” compared to “Healthy” dietary pattern at baseline was significantly associated with higher FMI-z, BMIz, and WC-z at follow-up. However, results not reaching statistical significance included comparisons between “Processed” or “Sweet” compared to “Healthy” dietary patterns at baseline with change in FMIz.

No statistically significant or unclear associations between dietary patterns and growth, body composition, or risk of obesity outcomes were reported in six articles. Among those studies, dietary patterns were derived from factor/cluster analysis in 4 articles and index-based scores in 3 articles (1 article used both methods). Components between dietary patterns widely varied and were less generalizable compared to the dietary patterns in the evidence described above. For example, the “Milks” dietary pattern at age 2y reported by Santos et al.^15^ was characterized by intake of only cow's milk and chocolate powder, and the “Treats” pattern by only crisps, sweets, and chocolate. Specificity of foods and beverages consumed in certain dietary patterns within studies also widely varied. For example, Oellingrath et al. 57 examined four different dietary patterns in 7^th^ graders (mean age 12.7y) with risk of overweight in 10^th^ grade. One of the dietary patterns was described as ‘dieting’ and characterized by foods and drinks associated with “weight control, like artificial sweetened drinks and other ‘light’ products”, whereas another was ‘varied Norwegian’, characterized by food items typical of a traditional Norwegian diet, including fruits and vegetables, brown bread, fish, water and regular breakfast and lunch, close to official nutritional guidelines.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed two separate conclusion statements to answer the question, ““What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?” based on their review of evidence for different dietary patterns consumed during childhood that related to growth, body composition, and risk of obesity outcomes. (Table 9)

Table 9 Conclusion statements and grades for dietary patterns consumed by children and adolescents and growth, body composition, and risk of obesity

Conclusion Statement | Dietary patterns consumed by children and adolescents that are characterized by higher intakes of vegetables, fruit, legumes, nuts, whole grains, fish/seafood, and dairy (low-fat, unsweetened) and lower intakes of red and processed meats, sugar-sweetened beverages, and sugar-sweetened or savory/salty snack foods are associated with favorable growth patterns, and lower adiposity and risk of obesity later in childhood up to early adulthood. This conclusion statement is based on evidence graded as limited. (Grade: Limited) | Dietary patterns consumed by children and adolescents that are characterized by higher intakes of red and processed meats, refined grains, sugar-sweetened beverages, sugar-sweetened or savory/salty snack foods, and fried potatoes and lower intakes of vegetables, fruit, and whole grains are associated with unfavorable growth patterns, and higher adiposity, and risk of obesity later in childhood and adulthood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
Grade | Limited | Limited
Body of Evidence | 62 articles: 3 randomized controlled trials, 59 prospective cohort studies | 62 articles: 3 randomized controlled trials, 59 prospective cohort studies
Consistency | Serious concerns due to considerable variation in the magnitude and significance of effect estimates | Substantial concerns due to considerable variation in the magnitude and significance of effect estimates
Precision | Serious concerns due to small sample sizes and wide confidence intervals | Serious concerns due to small sample sizes and wide confidence intervals
Risk of bias | Some concerns with risk of bias, including:; - Important confounding domains were not accounted for, particularly baseline anthropometry and race and/or ethnicity; - Potential for exposure misclassification; - Missing data not accounted for in several articles | Some concerns with risk of bias, including:; - Important confounding domains were not accounted for, particularly baseline anthropometry and race and/or ethnicity; - Potential for exposure misclassification; - Missing data not accounted for in several articles
Directness | Substantial concerns with directness of intervention studies; Some concerns with directness of observational studies | Some concerns with directness of observational studies
Generalizability | Relative to the U.S. population, outcomes were generalizable but there are some concerns with participants and dietary interventions or patterns being less generalizable. | Relative to the U.S. population, outcomes were generalizable but there are some concerns with participants and dietary patterns being less generalizable.

#### Assessment of evidence

This systematic review update includes 62 articles that met inclusion criteria and examined dietary patterns consumed by children and adolescents and growth, body composition, and/or risk of obesity. Dietary patterns were assessed using a variety of methods including investigator-assigned dietary intervention, indices or scores, factor/cluster analysis, latent class analysis, and reduced rank regression. Outcome measures varied across studies and included incidence of overweight/obesity, fat mass, lean or fat-free mass, BMI or BMI z-score, central adiposity/waist circumference or waist-hip-ratio, and weight/height. This body of evidence includes both large and small studies, including small studies with null findings, which makes publication bias less likely. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

##### Consistency

The direction of findings was split across the body of evidence: about one-third of the articles found that dietary patterns were associated with modestly favorable outcomes, another one-third reported dietary patterns were associated with modestly unfavorable outcomes, and the remaining one-third reported null or inconsistent findings. Some of the null findings could be explained by methodological inconsistencies such as methods used to examine dietary patterns, characteristics of dietary patterns, population studied and/or age of participants (e.g., ‘Milk” pattern at age 2 years), and unique outcomes (e.g., “corpulence”). Many reported effect sizes were relatively small, though magnitude varied across the body of evidence.

##### Precision

The interventions demonstrated adequate power/sample sizes and many of the observational studies had large sample sizes. However, many studies reported results that did not reach statistical significance (e.g., due to greater variance (e.g., wide confidence intervals including the null) and/or small sample sizes (e.g., n=81, n=158, n=216).

##### Risk of bias

Studies had numerous risks of bias across domains, which have the potential to influence the results reported. Many of the studies accounted for most of the key confounders, but residual confounding may still be expected. Of particular concern, 24% of included articles (13 of 55) did not control for anthropometry at study baseline. However, most of those studies accounted for a related variable such as height at another time point, or birthweight. Among the included articles, 27% (15 of 55) conducted diet assessments only once at baseline whereas 63% used repeated measures to assess diet during follow-up. However, only a few studies examined the relationship between change in dietary patterns and outcomes over follow-up. Few studies used dietary assessment methods that were not clearly validated in the population of interest, therefore, are also at higher risk of bias due to exposure classification. Some studies (9%, or 5 of 55) are particularly at higher risk of bias due to outcome measurement from relying upon self- or parent- reported weight and height to calculate BMI or other outcomes. Many of the articles did not account for missing data. (Table 11 and Table 12)

##### Directness

The interventions were not designed to directly compare the relationship between dietary patterns and growth, body composition and risk of obesity. One trial was designed to treat asthma, and not specifically examine the relationship between different dietary patterns and the outcomes of interest in this review. In another trial, the comparisons between intervention arms more accurately reflected differences in fat and fiber consumption than dietary patterns overall. Lastly, the comparator in the third trial was different levels of adherence to the mDQI scores. Several observational studies had issues with directness from either the populations, intervention, comparators, and/or outcomes of interest relative to this systematic review question.

##### Generalizability

The body of evidence included studies from a total of 24 countries with similar HDI classification as the U.S. Although many of the studies were conducted in European countries, several (6 of 55) studies were conducted in the United States and/or examined dietary patterns that are applicable to those consumed by Americans.

Table 10 Evidence in children and adolescents examining the relationship between dietary patterns consumed and growth, body composition, and risk of obesity^a^

Study Characteristics | Intervention/exposure and comparator | Results | Methodological considerations
Asodeh, 2023 ^24^; Iran, RCT; Analytic N=70; Selection data: Enrolled only female adolescents with metabolic syndrome who were not on a diet in the past 3 months | Age at Dietary Pattern: 14y, mean (13 to 18y); Mediterranean diet: Consumed similar vegetables, fruits, grains, meat and meat products, sugar, but significantly higher total fat, MUFA, and fiber than Control group, which was assigned to usual dietary recommendations (consumed significantly less total fat, MUFA, and fiber than Mediterranean group); Method: RCT | Results at age(s) F/U: 12 wks:; - BMI, mean ± SE: −0.08 ±0.09 v. −1.1 ±0.09; p<0.001; - WC, mean ± SE: −0.2 ±0.2 v. −2.9 ±0.2; p<0.001; - Weight, mean ± SE: −0.2 ±0.2 v. −2.7 ±0.2; p<0.001 | - Intensity was relatively high: control group was only given verbal instruction; Funding: Tehran Endocrine and Metabolism Research Center and the Tehran University of Medical Science
Lee 2020 ^49^; South Korea, RCT; Analytic N=104; Selection data: Enrolled only those with moderate to severe obesity (BMI ≥ 97th %tile); Excluded those with mental illness, learning disabilities or did not complete the intervention | Age at Dietary Pattern: 10y, mean; modified Diet Quality Index-International (DQI-I) [Kim, 2003]: Positive (Adequacy): Vegetable group; Fruit group; Grain group; Fiber; Protein; Iron; Calcium; Vitamin C; Negative: Total Fat, SFA, Cholesterol; Sodium; Empty-Energy Foods. Neutral: Carbohydrate: Protein: Fat Ratio; PUFA: MUFA: SFA ratio; Variety; Method: Index/Score Analysis, RCT | Results at age(s) F/U: 24wk:; - mDQI & Δ zBMI: −0.02 v. −0.07; p-trend=0.123; - mDQI & ΔFM (kg): 0.64 v. −0.04; p-trend= 0.232; - mDQI & Δ%FM: −0.91 v. −1.47; p-trend= 0.288; - mDQI & ΔWeight (kg): 3.43 v. 2.51; p-trend=0.187; - mDQI &AHt (cm): 3.03 v. 2.88; p-trend=0.565 | - 38% dropout rate;; - Possible selection bias;; - Relative intense delivery of intervention; Funding: Korea Centers for Disease Control and Prevention
Papamichael, 2019 ^59^; Greece, RCT; Analytic N=64; Selection data: Included only those with asthma; excluded LFU/discontinued | Age at Dietary Pattern: 5 to 12 y; Mediterranean diet + fatty fish vs. Control group: Higher in Legumes, Lean fish, and Fatty fish; Similar consumption of Vegetables; Fruit; Starch; Seafood; Meat; Nuts; Olive oil; Dairy products; Fats; Fast food; Sweets; Savour snacks; Soft drinks; Method: RCT | Results at age(s) F/U: 6 mo:; - Intervention v. Control & BMI, 18.70 [3.90] v. 18.73 [3.84]; p-trend=0.98 | - Primary outcome was asthma and BMI was to confirm differences between groups; KIDMED adherence differed by intervention group at follow-up; Controlled other aspects of the intervention; Funding: None
Agnihotri, 2021 ^2^; Norway; Norwegian Mother, Father and Child Cohort Study (MoBa); Analytic N=14989 Selection data: Enrolled mothers during pregnancy; Excluded if missing data from Medical Birth Registry of Norway; missing questionnaire data during mother’s pregnancy; multiple pregnancies; additional pregnancies by same mother; extreme intake during pregnancy; child age <7 or >9.5 at outcome; missing outcome data; anthropometric data outside of +/− 4 SD | Age at Dietary Pattern: 3 y, 7 y; New Nordic Diet (NND) score [Agnihotri, 2020] at age 3 y: Positive: Vegetables >5 times/wk; Fruit >7 times/wk; Potatoes (more than rice/pasta); Fish >2.12 times/wk; Milk (more milk than juice); Negative: Sweetened beverages (<2.5 times/wk); NND, at age 7 y: Positive: Cabbages; Root Vegetables; Fruits (Local apples, pears, grapes); Potatoes (more than rice/pasta); Whole grain bread; Oatmeal; Fish; Milk (more than fruit juice); Water (more than sweetened beverages); Method: Index/Score Analysis | Results at age(s) 8y:; NND at 3 y & OW, low, OR: 1.00, ref; - Medium, OR: 1.10, 95% CI: 0.96, 1.26; p-trend=0.177; - High, OR: 1.01, 95% CI: 0.87, 1.18; p-trend=0.887; - Per 1-pt, OR: 0.99, 95% CI: 0.96, 1.03; p-trend=0.775; NND at 7 y & OW, low, OR: 1.00, ref; - Medium, OR: 1.05, 95% CI: 0.93, 1.20; p-trend=0.421; - High, OR: 1.12, 95% CI: 0.97, 1.29; p-trend=0.117; - Per 1-pt, OR: 1.02, 95% CI: 0.99, 1.05; p-trend=0.236 | - Did not account for: Anthropometry (adjusted for BW), Race/Ethnicity, Physical activity; - Did not account for energy intake in analyses; - Parent-reported Ht & Weight of child at 8 y used to calculate BMI for OW; Funding: Norwegian Ministry of Health and Care Services, Ministry of Education and Research
Aljahdali, 2022 ^19^; Mexico; Early Life Exposure in Mexico to Environmental Toxicants (ELEMENT); Analytic N=574; Selection data: Enrolled pregnant mothers from low-middle income prenatal clinics; Included those who attended at least one of three follow-up visits; had data for at least one of eight cardiometabolic risk factors (WC, SBP, DBP, fasting glucose, fasting TG, fasting HDL-C, fasting insulin, and HOMA-IR); had dietary information | Age at Dietary Pattern: 8 to 14 y, mean 10.3; 10 to 18 y, mean 14.5y; 12 to 21 y, mean 16.4; Alternate Med Diet Score (aMED) [Fung 2005] Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; DASH Score [Fung 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method: Index/Score Analysis | Results at age(s) 12 to 21 y, mean 16.4y:; DASH Score & WC; - Q1, β: 1, ref; - Q2, p: 0.5597 (0.2438); p-trend=0.0219; - Q3, β: −0.03468 (0.2509); p-trend= 0.8901; - Q4, β: −0.01519 (0.2811); p-trend=0.9569; - Continuous, β: −0.01519 (0.02697); p-trend= 0.5735; aMED & WC; - Q1, β: 1, ref; - Q2, β: −0.1404 (0.2602); p-trend= 0.5896; - Q3, β: −0.3892 (0.2458); p-trend= 0.1136; - Q4, p: 0.1856 (0.3214); p-trend=0.5638; - Continuous, β: −0.03578 (0.06906); p-trend= 0.6045 | - Did not account for: Race and/or Ethnicity (100% Mexican-heritage, birth cohort); Anthropometry at baseline was not accounted for in T2D or CVD results; - FFQ was not formally validated;; - Unclear methods used to derive single estimate from multiple times; Time points used in analyses are unclear; - Post-exposure intervention of maternal Ca+ supplementation trial in subset; Results not be generalizable to those not from Mexico City; Funding: U.S. Environmental Protection Agency; National Institute for Environmental Health Sciences; National Institute of Public Health/Ministry of Health of Mexico
Ambrosini, 2016 ^20^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=4729; Selection data: Excluded those with missing data; other reasons NR | Age at Dietary Pattern: 7 y; “DP1”: Higher in confectionery and chocolate, cakes and biscuits, SSBs, low-fiber bread, and lower in fruit, vegetables, high-fiber bread, cereals; “DP2”: Higher in sugar-sweetened beverages, fruit juices, ready-to-eat breakfast cereals, and lower in whole milk, margarines and oils, cheese, crisps; Method: Reduced rank regression (RRR) | Results at age(s) 15y:; FMIz; - DP1, β: 0.04, 95% CI: 0.01,0.08, p=0.028; - DP2, β: −0.03, 95% CI: −0.07, 0.02, p=0.22; Excess adiposity; - DP1, β: 1.11, 95% CI: 0.97, 1.28, p=0.14; - DP2, β: 0.92, 95% CI: 0.78, 1.09, p=0.34 | - Did not account for: Race/ethnicity; - Diet assessed once at baseline;; - Did not describe or fully account for selection into analyses or missing data; Funding: The United Kingdom Medical Research Council; Wellcome Trust; University of Bristol
Arenaza, 2020 ^21^; Spain; EFIGRO study; Analytic N=81; Selection data: Enrolled only children with Ob/OW; Excluded non-completers; missed > 50% of lifestyle education sessions; < 2, 24 h-recalls at baseline and post-intervention | Age at Dietary Pattern: 9 to 11 y; Mediterranean Diet Quality Index for children and adolescents (KIDMED) [Serra-Majem, 2004]: Positive: Vegetables; Pulses; Fruit/Fruit Juice; Nuts; Pasta or Rice; Fish; Yogurt/Cheese; Olive Oil; Negative: Sweets and Candy; Method: Index/Score Analysis | Results at age(s) F/U: 22 wks:; - ΔKIDMED & ΔFMI, r: 0.004; p-trend=0.976; - ΔKIDMED & Δ Hepatic fat (%), r: 0.191; p-trend=0.134; - ΔKIDMED & Δ Abdominal fat (kg), r: −0.080; p-trend=0.535 | - Did not account for: Anthropometry (adjusted for Ht),Race/Ethnicity, Physical activity, SEP; - Reported differences with exercise in intervention group vs. control; Foods/beverages not described in Healthy Diet Indicator data; Funding: Spanish Ministry of Industry and Competitiveness, European Regional Development Funds, University of the Basque Country
Arruda, 2021 ^22^; Brazil; Longitudinal Study on Sedentary Behavior, Physical Activity, Eating Habits and Health of Adolescents - LONCAAFS; Analytic N=773; Selection data: Enrolled 6th graders in municipality of Joao Pessoa; Excluded those <10 and >14 y, with disability limiting PA or response to questionnaires, who were pregnant, with lack of anthropometric measurements, lack of 24-h recall data, LFU | Age at Dietary Pattern: 10 to 14 y; ‘Traditional’: positively correlated with intakes of basic food groups, beans and meat; ‘Snacks’: positively correlated with intake of processed meats, butters and margarines, breads and breakfast cereals, cheeses, and coffee and teas; ‘Western’: positively correlated with intake of sweets, pastries, sweetened drinks, cheese; negatively with coffee and teas; Method: Factor/Cluster Analysis | Results at age(s) 13 to 17y:; zBMI; - ‘Traditional’: β=−0.013, 95% CI: −0.034, 0.007; - ‘Snacks’: β=−0.014, 95% CI: −0.033, 0.005; - ‘Western’: β=0.024, 95% CI: 0.001,0.047 | - Did not account for: Race/ethnicity (Brazilian 6th graders); Funding: São Paulo Research Foundation (FAPESP)
Asghari, 2016 ^23^; Iran; Tehran Lipid and Glucose Study; Analytic N=424; Selection data: Excluded those with incomplete/missing diet or outcome data; with MetS, HTN, High TG/BP/FPG, Low HDL, or Abdominal Ob at baseline | Age at Dietary Pattern: 13.6y, mean; 6 to 18y; DASH score [Fung, 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Q4 v. Q1 ref had higher vegetables (2.1×), fruits (2.4×), nuts, legumes, and seeds (1.5×), whole grains (1.5×), low fat dairy (0.6×), lower red and processed meat (0.5×), sweetened beverages (1.6×), and sodium (0.3×); Method: Index/Score Analysis | Results at age(s) F/U: 3.6y (~age 17 y): DASH & BMI, no association (data NR); DASH & High-WC, Q1, ref; - Q2, OR: 0.63, 95% CI: 0.29, 1.35; - Q3, OR: 0.52, 95% CI: 0.24, 1.14; - Q4, OR: 0.35, 95% CI: 0.14, 0.89; - p-trend=0.047; DASH & mean [SD] WC:; - Q1: 79.8 [0.6];; - Q2: 80.0 [0.6];; - Q3: 79.1 [0.6];; - Q4: 78.9 [0.7], p=.503 | - Did not account for: Race/ethnicity (Iranian), SEP; - Diet assessed using a validated 168-item FFQ at baseline only; Funding: National Research Council of the Islamic Republic of Iran and the Research Institute for Endocrine Sciences, Shahid Beheshti University of Medical Sciences
Bawaked, 2020 ^25^; Spain; INMA (Infancia y Medio Ambiente [Environment and Childhood]) birth cohort; Analytic N=1480; 1256 BMI, 1248 WC; Selection data: Included mothers at least 16y old, delivering at referene hospital, Spanish/regional language, singelton pregnancy without assisted conception, children with relevant data (PA, sedentary activity, dietary, BMI/WC) | Age at Dietary Pattern: 4y; UPF (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Carbonated drinks, processed meat, biscuits [cookies], candy [confectionery], ‘instant’ packaged soups and noodles, sweet or savory packaged snacks, and sugared milk and fruit drinks.; Method: Index/score analysis | Results at age(s) 7y:; Growth/Body composition: UPF (High, ref) & BMIz; - Med UPF, B: −0.04, 95% CI: −0.15, 0.06; - Low UPF, B: −0.10, 95% CI: −0.20, 0.01; - p=0.07; UPF (High, ref) & WC; - Med. UPF, B: −0.05, 95% CI:−0.18, 0.07; - Low UPF, B: −0.08, 95% CI: −0.21,0.04; - p=0.18 | - Did not account for: Race and/or ethnicity; Physical activity (but modelled as IV of interest); TEI; - Diet assessed only once via FFQ at age 4y for past 12mo; Misclassification possible; Funding: Instituto de Salud Carlos III; EU Commission; Generalitat Valenciana; Generalitat de Catalunya-CIRIT; Department of Health of the Basque Government; Provincial Government of Gipuzkoa; Fundació La marató de TV3
Bekelman, 2021 ^26^; United States; Exploring Perinatal Outcomes in Children (EPOCH) study; Analytic N=581; Selection data: Excluded those with missing data on BMI, dietary intake, GDM exposure, sex, household income and race/ethnicity at Visit 1; some children exposed to GDM during utero | Age at Dietary Pattern: 10.4y, mean; Healthy Eating Index (HEI-2010) [Guenther 2013] : Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; Alternate Med Diet Score (aMED) [Fung 2005]: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat.; alternate DASH Score [Appel, 1997]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; Negative: Red and Processed Meat; Sweetened beverages; MUFA+PUFA; Sodium; Method: Index/Score Analysis | Results at age(s) 16.7y, mean:; HEI-2010 ♀ & BMI-trajectory; - per-10pt, β: −0.64, 95% CI: −1.11, −0.18; p-trend=0.007; HEI-2010 ♂ & BMI-trajectory; - per-10pt, β: 0.04, 95% CI: −0.48, 0.56; p-trend=0.87; aMED ♀ & BMI-trajectory; - β: −0.19, 95% CI: −0.51,0.13; p-trend=0.24; aMED ♂ & BMI-trajectory; - β: 0.07, 95% CI: −0.29, 0.43; p-trend=0.69; DASH ♀ & BMI-trajectory; - β: 0.28, 95% CI: −0.34, 0.89; p-trend=0.38; DASH ♂ & BMI-trajectory; - β: 0.55, 95% CI: −0.10, 1.20; p-trend=0.10 | - Did not account for: Anthropometry at baseline (within outcome), Physical activity; Funding: NIH
Biazzi, 2017 ^27^; Brazil; n/a; Analytic N=458 (n=1158 baseline); Selection data: Excluded those with extreme dietary intake (outlier) | Age at Dietary Pattern: 7 to 10 y; ‘DP I’: Rice; Leafy vegetables; Cooked beans; Beef/poultry; ‘DP II’: Salty snacks, French fries, fast-food, Sugary beverages; ‘DP III’: Cooked and leafy vegetables; Fruits; Fruit juices; Pasta; Milk; Cheese; ‘DP IV’: Milk; Coffee with milk, Cheese; Breads/biscuits; Method: Factor/Cluster Analysis | Results at age(s) 12 to 15y:; AzBMI; - DP I: Coeff.: 0.01; Effect size: 0.00, p=0.92; - DP II: Coeff.: 0.02; Effect size: 0.00, p=0.45; - DP III: Coeff.: −0.04; Effect size: 0.00, p=0.19; - DP IV: Coeff.: 0.05; Effect size: 0.01, p=0.07 | - Did not account for: Race/Ethnicity; - Diet assessed using 1-d recall questionnaire at baseline and F/U; Accounted for missing data via testing those with F/U v. LFU; Funding: Brazilian National Council for Scientific and Technological Development
Buckland, 2022 ^28^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=1940 17y; 1961 24y; Selection data: Excluded those diagnosed with DM, on insulin tx, or fasting glucose ≥ 7 mmol/L; those with extreme outliers on CMR score components; incomplete dietary data | Age at Dietary Pattern: 7 y; Children’s relative Mediterranean-style diet score (C-rMED) [Buckland, 2022]: Positive: Fruit (including nuts and seeds), vegetables (excluding potatoes), pulses, cereals and cereal products, dairy products, legumes, fish and seafood, MUFA+PUFA/SFA. Negative: meat and meat products; Method: Index/Score Analysis | Results at age(s) 17y, 24y:; BMI at age 17y; - 7y: OR: 0.95, 95% CI: 0.85, 1.05; - 10y: OR: 1.00, 95% CI: 0.90, 1.16; - 13y: OR: 0.95, 95% CI: 0.85, 1.05; BMI at age 24y; - 7y: OR: 0.92, 95% CI: 0.83, 1.02; - 10y: OR: 0.94, 95% CI: 0.84, 1.04; - 13y: OR: 0.83, 95% CI: 0.75, 0.92; FMI at age 17y; - 7y: OR: 0.92, 95% CI: 0.82, 1.02; - 10y: OR: 0.95, 95% CI: 0.85, 1.07; - 13y: OR: 0.88, 95% CI: 0.79, 0.98; FMI at age 24y; - 7y: OR: 0.95, 95% CI: 0.85, 1.05; - 10y: OR: 0.91, 95% CI: 0.81, 1.01; - 13y: OR: 0.81, 95% CI: 0.73, 0.90; WC at age 24y; - 7y: OR: 0.90, 95% CI: 0.81, 1.00; - 10y: OR: 0.89, 95% CI: 0.81, 0.99; - 13y: OR: 0.87, 95% CI: 0.79, 0.97 | - Did not account for: Anthropometry at baseline, Race/Ethnicity; Funding: UK Medical Research Council and Wellcome, University of Bristol, Wellcome Trust and MRC, The British Heart Foundation, British Heart Foundation Research Fellowship, MRC Career Development Award
Bull and Northstone, 2016 ^29^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=2311; Selection data: Excluded those with missing data on CV measures, dietary patterns info at all time points, and covariable data | Age at Dietary Pattern: 7, 10, and 13y; “Healthy”, ref: Non-white bread, reduced-fat milk, cheese, yoghurt and fromage frais, butter, breakfast cereal, rice, pasta, eggs, fish, vegetable and vegetarian dishes, soup, salad, legumes, fruit, crackers and crispbreads, high-energy-density sauces (e.g. mayonnaise), fruit juice, water; “Processed”: Processed meat, pies and pasties, coated and fried chicken and white fish, pizza, chips, baked beans and tinned pasta, chocolate, sweets, sugar, diet and regular fizzy drinks; “Traditional”: Red meat, poultry, potatoes, vegetables, starch-based products, low-energy-density sauces, puddings, tea, coffee; “Packed Lunch”: White bread, margarine, ham and bacon, sweet spreads, salty flavourings, crisps, biscuits, diet squash, tea, coffee; Method: Factor/Cluster Analysis | Results at age(s) 17y:; High BMI; - 7y ‘Processed’, OR: 1.6, 95 % CI: 1.01,2.55; p=0.05; - 10y ‘Processed’, OR: 0.8, 95 % CI: 0.52,1.23; p=0.31; - 13y ‘Processed’, OR: 1, 95 % CI: 0.63,1.59; p=1; - 7y ‘Traditional’, OR: 1.22, 95 % CI: 0.75,1.98; p=0.42; - 10y ‘Traditional’, OR: 0.82, 95 % CI: 0.52,1.27; p=0.37; - 13y ‘Traditional’, OR: 1.41, 95 % CI: 0.87,2.28; p=0.16; - 7y ‘Packed-lunch’, OR: 1.96, 95 % CI: 1.22,3.13; p=0.005; - 10y ‘Packed-lunch’, OR: 0.97, 95 % CI: 0.62,1.52; p=0.89; - 13y ‘Healthy’, OR: 1.15, 95 % CI: 0.77,1.72; p=0.51 | - Did not account for: Anthropometry (adjusted for BW, GA), Race/ethnicity, Physical activity;; - Diet assessed once each age time point; Unclear if diet assessment methods were valid/reliable; Serious concerns with accuracy of data tables; Funding: The United Kingdom Medical Research Council; Wellcome Trust; University of Bristol
Chan She Ping-Delfos, 2015 ^30^; Australia; Western Australian Pregnancy Cohort; Analytic N=1419; Selection data: Excluded those with missing data, implausible energy intake | Age at Dietary Pattern: 14 y; Dietary Guideline Index for Children and Adolescents (DGI-CA): Fruit/100% fruit juice, vegetables and legumes, breads and cereals, wholegrain bread relative to total, meat and alternatives (excluding processed meat); dairy products: reduced- or low-fat dairy, water as a beverage, healthy fats: total fats, <3/d ‘extra foods’; Method: Index/Score Analysis | Results at age(s) 17y:; - BMI, β: 0.0007, 95% CI: 0.00 007, 0.0012; p=0.029; - WC, β: −0.0003, 95% CI: −0.0006, −0.00004; p=0.026; - WHR, β: 0.009, 95% CI: −0.033, 0.051; p=0.680 | - Did not account for: Race/ethnicity; - Diet assessed once at baseline with record validated in adults only; Funding: University of Western Australia; the Faculty of Medicine, Dentistry and Health Sciences at the University of Western Australia; the Telethon Kids Institute; the Women and Infants Research Foundation; Curtin University; and the Raine Medical Research Found
Chang, 2021 ^31^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=9025; Selection data: Pregnant women with an expected delivery date between April 1991 and Dec. 1992; Excluded those with missing dietary data and/or outcome data | Age at Dietary Pattern: 7 y; UPF (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Soft drinks; sweet or savoury packaged snacks; ice cream, chocolate, candies; massproduced packaged breads and buns; margarines and spreads; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; flavoured and/or artificial sweetened yoghurt; Method: Index/Score Analysis | Results at age(s 24y; BMI: Q5 vs. Q1 (ref), HR: 1.18, 95% CI: 0.78, 1.57; - Q2, HR: 0.06, 95% CI: −0.10, 0.23; - Q3, HR: 0.006, 95% CI: −0.16, 0.17; - Q4, HR: 0.02, 95% CI: −0.15, 0.19; - Q5, HR: 0.08, 95% CI: −0.09, 0.24; zBMI, Q1, HR: 0, ref; - Q2, HR: 0.06, 95% CI: −0.01, 0.13; - Q3, HR: 0.03, 95% CI: −0.04, 0.10; - Q4, HR: 0.05, 95% CI: −0.02, 0.12; - Q5, HR: 0.05, 95% CI: −0.02, 0.12; BF%: Q5 vs. Q1, HR: 1.53, 95% CI: 0.81, 2.25; - Q2, HR: 0.65, 95% CI: −0.01, 1.30; - Q3, HR: 0.67, 95% CI: 0.02, 1.32; - Q4, HR: 1.02, 95% CI: 0.35, 1.67; - Q5, HR: 1.47, 95% CI: 0.81, 2.13; FMI: Q5 vs. Q1, HR: 0.78, 95% CI: 0.46, 1.08; - Q2, HR: 0.08, 95% CI: −0.09, 0.26; - Q3, HR: 0.11, 95% CI: −0.06, 0.28; - Q4, HR: 0.17, 95% CI: −0.01, 0.34; - Q5, HR: 0.27, 95% CI: 0.09, 0.45; Fat mass, kg, Q1 HR: 0, ref; - Q2, HR: 0.11, 95% CI: −0.31, 0.52; - Q3, HR: 0.10, 95% CI: −0.32, 0.51; - Q4, HR: 0.20, 95% CI: −0.22, 0.62; - Q5, HR: 0.51, 95% CI: 0.08, 0.93; LMI, Q1, HR: 0, ref; - Q2, HR: 0.005, 95% CI: −0.06, 0.07; - Q3, HR: 0.009, 95% CI: −0.06, 0.07; - Q4, HR: −0.01, 95% CI: −0.08, 0.05; - Q5, HR: −0.01, 95% CI: −0.08, 0.05; Lean mass, kg, Q1, HR: 0, ref; - Q2, HR: 0.13, 95% CI: −0.16, 0.42; - Q3, HR: −0.01, 95% CI: −0.30, 0.28; - Q4, HR: −0.07, 95% CI: −0.36, 0.23; - Q5, HR: 0.07, 95% CI: −0.23, 0.37; WC in cm: Q5 vs. Q1, HR: 3.08, 95% CI: 2.08, 4.06; - Q2, HR: 0.26, 95% CI: −0.14, 0.66; - Q3, HR: 0.03, 95% CI: −0.36, 0.42; - Q4, HR: 0.22, 95% CI: −0.18, 0.62; - Q5, HR: 0.16, 95% CI: −0.25, 0.56; Weight, kg: Q5 vs. Q1 (ref), HR: 3.66, 95% CI: 2.18, 5.12; - Q2, HR: 0.35, 95% CI: 0.007, 0.69; - Q3, HR: 0.30, 95% CI: −0.03, 0.63; - Q4, HR: 0.34, 95% CI: −0.007, 0.68; - Q5, HR: 0.30, 95% CI: −0.04, 0.65 | - Did not account for: n/a (all accounted for); - Diet assessed with 3d food diary at multiple points (age 7 y; age 10y, age 13y); Funding: UK Medical Research Council (MRC); Wellcome Trust; University of Bristol
Choy, 2020 ^32^; Samoa; Ola Tuputupua’e “Growing Up” cohort study; Analytic N=214; Selection data: Excluded those with severe physical or cognitive impairments, not of Samoan ethnicity, lost to f/up, missing data | Age at Dietary Pattern: 2 to 4 y; ‘Modern’: High intakes of french fries, unprocessed red meat, potatoes/sweet potatoes, cereals, noodles, and fruit juices, and low intakes of breadfruit and taro; ‘Neotraditional’: high intakes of fruits, vegetables, tomatoes, banana-based dishes, and soups; Method: Factor/Cluster Analysis | Results at age(s) 4 to 6y:; ‘Modern’ & zBMI 2017; - Consistently low: β=1, ref; - Low to high: β=0.12, 95% CI: −0.19, 0.42; - High to low: β=0.10, 95% CI: −0.21, 0.41; - Consistently high: β=0.34, 95% CI: 0.03, 0.65; p-value = 0.03; ‘Neotraditional’ & zBMI 2017; - Consistently low: β=1, ref; - Low to high: β=0.02, 95% CI: −0.28, 0.31; - High to low: β=−0.08, 95% CI: −0.39, 0.23; - Consistently high: β=−0.11, 95% CI: −0.43, 0.20; ‘Modern’ & zBMI Δ 2015–2017; - β=ES, 95% CI: LL, UL; - Consistently low: β=1, ref; - Low to high: β=0.20, 95% CI: −0.12, 0.52; - High to low: β=0.13, 95% CI: −0.19, 0.46; - Consistently high: β=0.36, 95% CI: 0.04, 0.69; p-value = 0.03; ‘Neotraditional’ & zBMI Δ 2015–2017; - Consistently low: β=1, ref; - Low to high: β= −0.028, 95% CI: −0.34, 0.29; - High to low: β= −0.10, 95% CI: −0.43, 0.22; - Consistently high: β= −0.12, 95% CI: −0.45, 0.21; ‘Modern’ & Weight-z Δ 2015–2017; - Consistently low: β=1, ref; - Low to high: β=0.05, 95% CI: −0.18, 0.28; - High to low: β=0.00, 95% CI: −0.23, 0.24; - Consistently high: β=0.13, 95% CI: −0.10, 0.37; ‘Neotraditional’ & Weight-z Δ 2015–2017; - Consistently low: β=1, ref; - Low to high: β=0.02, 95% CI: −0.21, 0.24; - High to low: β= −0.04, 95% CI: −0.27, 0.19; - Consistently high: β= −0.08, 95% CI: −0.32, 0.16; ‘Modern’ & Ht z-score z Δ 2015–2017; - Consistently low: β=1, ref; - Low to high: β= −0.10, 95% CI: −0.37, 0.18; - High to low: β= −0.12, 95% CI: −0.40, 0.16; - Consistently high: β= −0.15 95% CI: −0.43, 0.13; ‘Neotraditional’ & Ht z-score Δ 2015–2017; - Consistently low: β=1, ref; - Low to high: β=0.09, 95% CI: −0.18, 0.35; - High to low: β= 0.06, 95% CI: −0.21,0.34; - Consistently high: β= 0.01, 95% CI: −0.27, 0.29 | Did not account for: Anthropometry at baseline for Δ 2015–2017; Sample size <300; Underpowered according to post-hoc power calculation for ‘Modern’ or ‘Traditional’ patterns & zBMI; Funding: Yale School of Public Health, NIMHD, U.S. Fulbright Graduate Student Research Fellowship, Brown University School of Public Health, Brown University Population Studies and Training Center, NHLBI, Fogarty Global Health Equity Scholars Program
Costa, 2019 ^35^; Brazil; n/a (F/U cohort from RCT); Analytic N=315; Selection data: Excluded HIV+ mothers, those with congenital/NICU stay, and not from maternity ward of low-income hospital/population in urban Brazil | Age at Dietary Pattern: 4y; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) by % TEI contribution: Highest in Sweets (candy, chocolate, ice cream); Breads; Biscuits (crackers and cookies); Soft drinks (soda, sweetened juice and sports drinks); Powdered chocolate; Savory chips and Salty snacks; Processed meat; Sugary Milk beverages; Instant noodles, dehydrated soup, mayonnaise, dressing/sauces; Breakfast cereals (lowest mean intake at age 4y); Method: Index/Score Analysis: UP, Nova | Results at age(s) 8y:; Growth/Body composition:; UPF per 10% &; - Δ SFT, β: 0.04, 95%CI: −0.05, 0.14; p=0.377; - Δ BMI, β: 0.00, 95% CI: −0.02, 0.01; p=0.736; - Δ WC, β: 0.06, 95% CI: 0.01,0.13; p=0.046; - Δ Waist-to-Height Ratio, β: 0.00, 95%CI: 0.00, 0.00; p=0.089; - Δ WC, β: 0.06, 95% CI: 0.01,0.13; p=0.046; - Δ Waist-to-Height Ratio, β: 0.00, 95%CI: 0.00, 0.00; p=0.089 | - Did not account for: Age, Race/Ethnicity, Physical activity (but screen time); - Diet assessed with 24h recall at 4 and 8y from self-report with help of parent;; Funding: Brazil National Council for Scientific and Technological Development
Costa, 2021 ^161^; Brazil; 2004-Pelotas-Brazil Birth Cohort; Analytic N=3128; Selection data: Newborns to mothers in urban Pelotas/Jardim within Gapao do Leao | Age at Dietary Pattern: 6y; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]): Sweet cookies; salty cracker; yogurt or milk drink; ham; mortadella; sausage; butter or margarine; mayonnaise; candies, lollipop or chewing gum; chocolate bar or bonbon; ice cream or popsicle; chocolate powder; sugar sweetened beverages; artificially sweetened beverages (light, diet or zero); artificial juice (powder or box); salty snacks; sandwich cookies; gelatin.; Method: Index/Score Analysis: UP, Nova | Results at age(s) 11y:; Growth/Body composition:; UPF, g & ΔFMI 6–11y:; - β: 0.14, 95% CI: 0.13, 0.15; p<0.001 (adjusted for non-UPF food sources); - β: 0.05, 95% CI: 0.04, 0.06; p<0.001 (adjusted for TEI) | - Did not account for: Age, Anthropometry at baseline (assessed change from 6–11y as main result); - Diet assessed via FFQ at 6y (parent-report) and 11y (parent-report w/ child help); Misclassification possible; - Moderate effect size per 100g increase in UPF was associated with 0.14 kg/m2 of FMI increase from 6 to 11y; 58% of effect of UPF on FMI due to mediation from TEI (42% direct effect of UPF on FMI); Funding: Wellcome Trust; Departamento de Cie^ncia e Tecnologia (DECI); Conselho Nacional de Desenvolvimento Cienti’fico e Tecnolo’gico-Brazil
Costa, 2022 ^34^; Brazil; 2015-Pelotas-Brazil Birth Cohort; Analytic N=3498; Selection data: Newborns to mothers in urban Pelotas/Jardim within Gapao do Leao | Age at Dietary Pattern: 2y; UPF (Nova food classification system, group 4 [Monteiro, 2019]) 9 sub-groups: i) Instant noodles 30%; (ii) Soft drinks 37%; (iii) Chocolate powder (in milk) 43%; (iv) Nuggets, hamburger or sausages 43%; (v) Salty snacks, packaged 46%; (vi) Candies, lollipops, chewing gum, chocolate or jelly 65%; (vii) Cookie (sandwich-type) or Sweet Biscuit 65%; (viii) Juice from can, box, or powder 67%; (ix) Yogurt 88%; Method: Index/Score Analysis: UP, Nova | Results at age(s) 4y:; Growth/Body composition:; UPF & BMI-age-z (BAZ),; - cont. β: 0.02, 95% CI: 0.01,0.03; p<0.001; - T1, ref; T2, β: 0.05, 95% CI: −0.01, 0.11; - T1, ref; T3, β: 0.01, 95% CI: −0.06, 0.07; p=0.207; - 6+ vs. ≤ 5 of 9 sub-groups, β: 0.09, 95% CI: 0.04, 0.14; p<0.001; UPF & L/HAZ; - cont. β: −0.03, 95% CI: −0.04, −0.02; p<0.001; - T1, ref; T2, β: −0.04, 95% CI: −0.08, 0.01; - T1, ref; T3, β: −0.06, 95% CI: −0.11, −0.01 ; p=0.023; - 6+ vs. < 5 of 9 sub-groups, β: −0.10, 95% CI: −0.14, −0.06; p<0.001 | - Did not account for: Age, TEI; - Diet assessed via FFQ at 2y and 4y; Misclassification possible due to UPF intake based on FFQ (Y/N of usually consuming 9 sub-groups); Outcomes objectively measured; Precise effects (narrow CI) when UPF analyzed continuously; Funding: Wellcome Trust; Conselho Nacional de Desenvolvimento Cienti’fico e Tecnolo’gico- Brazil; Fundação de Amparo a Pesquisa do Estado do Rio Grande do Sul; Children’s Pastorate; Bernard van Leer Foundation
Costa, 2023 ^36^; Portugal; Epidemiological Health Investigation of Teenagers in Porto (EPITeen); Analytic N=862; Selection data: Excluded those with missing or outliers of dietary/outcome data | Age at Dietary Pattern: 13y; ‘Lower intake’: lower consumption of majority food groups; ‘Healthier’: highest consumption of seafood, soup, vegetables/legumes, fruit, and added fats; ‘Dairy products’: highest consumption of dairies; ‘Fast food and sweets’: fast food, sweets and pastry, soft drinks and coffee or tea; Method: Factor/Cluster Analysis | Results at age(s) 21 y:; BMI, est. mean; - ‘Lower intake’, 23.7, 95% CI: 233, 24.2; - Healthier’, 23.1, 95% CI: 22.4, 23.8; - Dairy products’, 23.1, 95% CI: 22.6, 23.6; - Fast food and sweets’, 22.6, 95% CI: 21.9, 23.4; - p=0.029; FM, %, est. mean; - ‘Lower intake’, 20.8, 95% CI: 19.9, 21.7; - ‘Healthier’, 20.1, 95% CI: 18.8, 21.4; - Dairy products’, 19.8, 95% CI: 18.8, 20.8; - Fast food and sweets’, 18.8, 95% CI: 17.4, 20.2; - p=0.054; WC, cm, est. mean; - ‘Lower intake’, 79.3, 95% CI: 78.1, 80.4; - ‘Healthier’, 78.2, 95% CI: 76.5, 79.9; - ‘Dairy products’, 78.3, 95% CI: 77.0, 79.6; - ‘Fast food and sweets’, 76.9, 95% CI: 75.0, 78.7; - p=0.108 | - Did not account for: Race and/or Ethnicity, Physical activity; - Diet assessed at multiple time points (age 13y, 21y) using a FFQ validated in adults; No differences between those included or excluded due to LFU; Data on dietary patterns foods/food groups reported in separate article [Araujo, 2015: https://doi.org/10.1016/j.nut.2014.06.007]; Funding: Portuguese Foundation for Science and Technology; University of Porto
Cunha, 2018 ^37^; Brazil; n/a; Analytic N=1035; Selection data: Excluded those with pregnancy or physical disability, w/ obesity at baseline; Included 1st year high-school students from 4 private and 2 public urban schools | Age at Dietary Pattern: 15.7y, mean (13.5–19.5y); [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Sodas; Fruit drinks; Candies; Cookies; Chocolate milk beverages; Guarana (soda); Packed fruit juices; Ham; french fries; Sweet Pastries; Chocolate; Chips; Fried, filled rolls; Oven-baked rolls; Instant pasta; Ice cream; Jelly; Nuggets; Hamburger; Pizza; Hot dog; Cheese rolls; Method: Index/Score Analysis: UP, Nova | Results at age(s) 16.6y (14.4–19.8); 17.6y (15.3–20.9):; Growth/Body composition:; Q4 v. Q1 UPF associated with lower %BF at 3y F/U (values/data NR); Q4 v. Q1 UPF was associated with lower BMI at 3y F/U (values/data NR); No interaction between age and UPF & BMI (p=0.07); Under-reporting of UPF intake (coefficient=−0.94) and PA (coefficient=−1.0) associated with BMI at F/U | - Did not account for: Race and/or ethnicity, SEP; - Diet assessed only once via validated FFQ; Misclassification possible due to UPF intake based on FFQ; TEI was lower for those in Q4 of UPF intake (possible mediation); those in 4th Q of UPF at baseline had lower BMI & %BF compared to Q1; Funding: National Council for Scientific and Technological Development; Research Support Foundation of the State of Rio de Janeiro; Coordination for the Improvement of Higher Education Personnel
Diethelm, 2014 ^38^; Germany; DONALD (Dortmund Nutritional and Anthropometric Longitudinal Designed) Study; Analytic N=371; Selection data: Included those with 3d diet record at 4 times; full-term; data on education and BF | Age at Dietary Pattern: 6 to 7y; PCA 1 ‘Healthy’: Higher loadings for vegetables, whole-grain bread, rice/other grains, vegetable oil and low for sweetened beverages; PCA 2 ‘Pancakes & Potatoes’: High loadings for flour, dough; potatoes; eggs; increased eggs; APCA1 towards ‘Pancakes and Convenience foods’: Increased convenience foods; APCA2 towards ‘Traditional’: Increased flour, dough; potatoes; sasuages, cold cuts, high fat and decreased pasta; dressings dips gravy; potato products; RRR1: Higher baseline intake of canned or dried fruit, lower biscuits, pulses, cereals, whole grain bread, and cheese; ΔRRR1: Increased savoury snacks, dressings, dips, gravy; water; cheese; sausages, cold cuts, high fat; Decreased chocolate; dairy (sweetened; high-fat); meat (high fat); fruit (canned or dried); Method: RRR; Factor/Cluster Analysis | Results at age(s) 10 to 11y:; RRR1: T3 v. T1, 21% higher increase in BMI; p=0.0003; ΔRRR1: T3 v. T1, 34% higher increase in BMI; p=0.0002; PCA 1 & ΔBMI; - T1, 2.29, 95% CI: 2.05, 2.53; - T2, 2.19, 95% CI: 1.95, 2.43; - T3, 2.19, 95% CI: 1.95, 2.43; p-trend=0.7; ΔPCA 1 & ΔBMI; - T1, 2.25, 95% CI: 2.01, 2.50; - T2, 2.16, 95% CI: 1.93, 2.40; - T3, 2.25, 95% CI: 2.01, 2.49; p-trend=0.6; PCA 2 & ΔBMI; - T1, 2.26, 95% CI: 2.03, 2.50; - T2, 2.18, 95% CI: 1.93, 2.42; - T3, 2.21, 95% CI: 1.97, 2.45; p-trend>0.9; ΔPCA 2 & ΔBMI; - T1, 2.19, 95% CI: 1.95, 2.42; - T2, 2.31, 95% CI: 2.07, 2.56; - T3, 2.18, 95% CI: 1.94, 2.42; p-trend=0.5; RRR1: T3 v. T1, 60% higher increase in FMI; p<0.0001; ΔRRR1: T3 v. T1,74% higher increase in FMI; p<0.0001; PCA 1 & ΔFMI; - T1, 1.12, 95% CI: 0.87, 1.36; - T2, 1.04, 95% CI: 0.80, 1.27; - T3, 0.94, 95% CI: 0.70, 1.18; p-trend=0.4; ΔPCA 1 & ΔFMI; - T1, 1.04, 95% CI: 0.79, 1.28; - T2, 0.98, 95% CI: 0.74, 1.22; - T3, 1.08, 95% CI: 0.84, 1.32; p-trend=0.9; PCA 2 & ΔFMI; - T1, 1.14, 95% CI: 0.91, 138; - T2, 0.96, 95% CI: 0.72, 1.21; - T3, 0.97, 95% CI: 0.73, 1.21; p-trend=0.4; ΔPCA 2 & ΔFMI; - T1, 0.95, 95% CI: 0.71, 1.18; - T2, 1.14, 95% CI: 0.89, 1.38; - T3, 1.03, 95% CI: 0.79, 1.27; p-trend=0.7 | - Did not account for: Physical activity; - Diet assessed using 3d weighed records at 4 time points; Funding: Kompetenznetz Adipositas (Competence Network Obesity) funded by the Federal Ministry of Education and Research
Durao, 2017 ^39^; Portugal; Generation XXI; Analytic N=3473; Selection data: Excluded those with diseases that influence diet, missing data | Age at Dietary Pattern: 4y; ‘Energy-dense foods’ (EDF): Sweets, soft drinks, salty pastry, processed meat; ‘Snacking’: Snack foods, lower in fish, meat, eggs, rice, pasta, potatoes, vegetables; ‘Healthier’: Higher in vegetables, fish, and lower in energy dense foods; Method: Latent Class Analysis | Results at age(s) 7y:; OW/Ob; - ♀EDF, SS: 1.48, 95 % CI: 0.96, 2.29; - ♀Snacking, SS: 1.32, 95 % CI: 0.67, 2.58; - ♂EDF, SS: 3.15, 95 % CI: 1.54, 6.45; - ♂Snacking, SS: 1.91, 95 % CI: 0.65, 5.6; BMI; - ♀EDF, SS: 0.074, 95 % CI: 0.002, 0.146; - ♀Snacking, SS: 0.011, 95 % CI: −0.091, 0.114; - ♂EDF, SS: 0.021, 95 % CI: −0.055, 0.097; - ♂Snacking, SS: −0.001, 95 % CI: −0.104, 0.103; FM%; - ♀EDF, SS: 0.045, 95 % CI: −0.026, 0.116; - ♀Snacking, SS: 0.05, 95 % CI: −0.051, 0.151; - ♂EDF, SS: 0.02, 95 % CI: −0.053, 0.093; - ♂Snacking, SS: −0.004, 95 % CI: −0.004, 0.095; FMI; - ♀EDF, SS: 0.078, 95 % CI: 0.011, 0; WHR; - ♀EDF, SS: 0.108, 95 % CI: 0.028, 0.187; - vSnacking, SS: 0.051, 95 % CI: −0.061, 0.164; - ♂EDF, SS: 0.025, 95 % CI: −0.050, 0.1; - ♂Snacking SS: 0.069, 95 % CI: −0.033, 0.171 | - Did not account for: Race/ethnicity;; - Diet assessed once at baseline; Diet assessment record validated in adults only; Funding: Programa Operacional de Saúde (Regional Department of Ministry of Health); Portuguese Foundation for Science and Technology (FCT) and by the Calouste Gulbenkian Foundation; EDER from the Operational Programme Factors of Competitiveness—COMPETE and through
Durão, 2022 ^40^; Portugal; Generation XXI; Analytic N=1861 girls; 1962 boys; Selection data: Excluded those with conditions that affect dietary intake and celiac dz, incomplete data on PA and screen time at 4yrs, incomplete data on maternal BMI at 4yrs, no BP data at 10yrs | Age at Dietary Pattern: 4 y; ‘Energy-dense foods’ (EDF): high intakes of sweets, sugar-sweetened beverages, savory pastry, and processed meat.; ‘Snacking’: lower in foods usually consumed at lunch and dinner (e.g., vegetables on a plate, fish, meat, rice/pasta/potatoes), higher in intermediate foods typically eaten at snacking occasions; ‘Healthier’: higher consumption of fruit, vegetables, vegetable soup, and fish, with a lower consumption of EDF; Method: Latent Class Analysis | Results at age(s) 10y:; OW, ‘Healthier’: OR: 1, ref; ♀ ‘EDF’: OR: 1.48, 95% CI: 0.96, 2.29; ♀ ‘Snacking’: OR: 1.32, 95% CI: 0.67, 2.58; ♂ ‘EDF’: OR: 1.01, 95% CI: 0.66, 1.53; ♂ ‘Snacking’: OR: 1.04, 95% CI: 0.58, 1.86; Obesity, ‘Healthier’: OR: 1, ref; ♀ ‘EDF’: OR: 3.15, 95% CI: 1.54, 6.45; ♀ ‘Snacking’: OR: 1.91, 95% CI: 0.65, 5.60; ♂ ‘EDF’: OR: 1.16, 95% CI: 0.62, 2.18; ♂ ‘Snacking’: OR: 0.86, 95% CI: 0.36, 2.07; BMI, ‘Healthier’ ref; ♀ ‘EDF’: β: 0.074, 95% CI: 0.002, 0.146; ♀ ‘Snacking’: β: 0.011, 95% CI: −0.091, 0.114; ♂‘EDF’: β: 0.021, 95% CI: −0.055, 0.097; ♂‘Snacking’: β: −0.001, 95% CI: −0.104, 0.103; FM%, ‘Healthier’ ref; ♀ ‘EDF’: β: 0.045, 95% CI: −0.026, 0.116; ♀ ‘Snacking’: β: 0.050, 95% CI: −0.051, 0.151; ♂ ‘EDF’: β: 0.020, 95% CI: −0.053, 0.093; ♂ ‘Snacking’: β: −0.004, 95% CI: −0.004, 0.095; FMI, ‘Healthier’: β: 1, ref; ♀ ‘EDF’: β: 0.078, 95% CI: 0.011, 0.145; ♀ ‘Snacking’: β: 0.080, 95% CI: −0.016, 0.176; ♂ ‘EDF’: β: 0.029, 95% CI: −0.040, 0.098; ♂ ‘Snacking’: β: −0.007, 95% CI: −0.101,0.087; WHR, ‘Healthier’: β: 1, ref; ♀ ‘EDF’: β: 0.108, 95% CI: 0.028, 0.187; ♂ ‘Snacking’: β: 0.051, 95% CI: −0.061, 0.164; ♂‘EDF’: β: 0.025, 95% CI: −0.050, 0.100; ♂‘Snacking’: β: 0.069, 95% CI: −0.033, 0.171 | - Did not account for: Race/Ethnicity; - Diet assessed once at baseline; Diet assessment record validated in adults only; Funding: Health Operational Programme–Saúde XXI, Community Support Framework III, Regional Department of Ministry of Health, FEDER–COMPETE, the Foundation for Science and Technology–FCT, a Researcher Contract, Epidemiology Research Unit and Laboratory for Integra
Farhadnejad, 2018 ^41^; Iran; Tehran Lipid and Glucose Study; Analytic N=628; Selection data: Excluded those with extreme dietary intake (over/under outlier); missing info; on specific diets; or LFU | Age at Dietary Pattern: 14.1y, mean; 10 to 18 y; DASH score [Fung, 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Method: Index/Score Analysis | Results at age(s) F/U: 3y:; DASH Q5 v. Q1 & Ob: OR: 0.26, 95% CI: 0.15, 0.76; DASH & 3-y Δ BMI, mean (SD); - Q1, 2.1 (3.1); - Q2, 1.8 (2.4); - Q3, 1.5 (2.6); - Q4, 1.6 (2.2); - Q5, 1.4 (2.3); - p-trend=0.035; DASH Q5 v. Q1 & Central Ob: OR: 0.32, 95% CI: 0.14, 0.84; DASH & 3-y Δ WC, mean (SD); - Q1,5.4 (9.1); - Q2, 4.7 (8.0); - Q3, 4.0 (7.5); - Q4, 3.3 (7.7); - Q5, 2.8 (7.4); - p-trend=0.027 | - Did not account for: Anthropometry at baseline, Race/ethnicity (NR; all Iranian), SEP, Physical activity; Funding: NR
Fernandez-Alvira, 2017 ^42^; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain; IDEFICS (Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS) study; Analytic N=8341; Selection data: Excluded those with missing data | Age at Dietary Pattern: 2 to 9 y; ‘Processed’: Higher takeaway and high-fat foods, such as savoury pastries, fritters, pizza as main dish, fried potatoes, hamburger, hot dog, kebab and wraps, and lowest scores for products such as wholemeal bread, cooked vegetables, raw vegetables, and fresh fruits without added sugar; ‘Sweet’: Higher sugar-rich products, like chocolate- or nut-based spread, sweetened drinks, fruit juices, diet drinks, candies, loose candies, marshmallows, and biscuits, packaged cakes, pastries and puddings, with the lowest scores for water, porridge, oatmeal, gruel, unsweetened cereals, muesli, raw vegetables, plain unsweetened milk and plain unsweetened yoghurt; ‘Healthy’: Higher low-fat foods, foods rich in vitamins and wholegrain foods, e.g. raw vegetables, fresh fruits without added sugar, porridge, oatmeal, gruel, unsweetened cereals, muesli and plain unsweetened milk, and the lowest values for high-fat, high-sugar products, such as fried potatoes, sweetened drinks, sweetened milk, mayonnaise and mayonnaise-based products, chocolate- or nut-based spread, crisps, corn crisps, popcorn, and biscuits, packaged cakes, pastries and puddings; Method: Factor/Cluster Analysis | Results at age(s) 4 to 11y (FU):; BMIzΔ; - ‘Processed’ v. ‘Healthy’ ref (baseline): 0.027, 95% CI: −0.008, 0.061; p=0.132; - ‘Sweet’ v. ‘Healthy’ ref (baseline): 0.033, 95% CI: −0.011, 0.077; p=0.147; - ‘Processed’ v. ‘processed’ at FU: 0.05, 95% CI: 0.006,0.093; p=0.024; - ‘Sweet’ v. ‘processed’ at FU: 0.015, 95% CI: −0.075, 0.105; p=0.741; - ‘Healthy’ v. ‘processed’ FU: 0.02, 95% CI: −0.062, 0.102; p=0.629; - ‘Processed’ v. ‘sweet’ FU: 0.079, 95% CI: 0.015, 0.143; p=0.016; - ‘Sweet’ v. ‘sweet’ FU: 0.05, 95% CI: −0.004, 0.103; p=0.069; - ‘Healthy’ v. ‘sweet’ FU: 0.04, 95% CI: −0.058, 0.139; p=0.421; - ‘Processed’ v. ‘healthy’ FU: 0.001, 95% CI: −0.042, 0.043; p=0.975; - ‘Sweet’ v. ‘healthy’ FU: 0.039, 95% CI: −0.030, 0.109; p=0.268; FMIzΔ; - ‘Processed’ v. ‘Healthy’ ref (baseline): 0.026, 95% CI: −0.004, 0.057; p=0.099; - ‘Sweet’ v. ‘Healthy’ ref (baseline): 0.019, 95% CI: −0.021, 0.058; p=0.357; - ‘Processed’ v. ‘processed’ FU: 0.052, 95% CI: 0.014, 0.090; p=0.007; - ‘Sweet’ v. ‘processed’ FU: 0.02, 95% CI: −0.058, 0.099; p=0.612; - ‘Healthy’ v. ‘processed’ FU: 0.04, 95% CI: −0.033, 0.113; p=0.281; - ‘Processed’ v. ‘sweet’ FU: 0.076, 95% CI: 0.019, 0.133; p=0.009; - ‘Sweet’ v. ‘sweet’ FU: 0.03, 95% CI: −0.017, 0.078; p=0.213; - ‘Healthy’ v. ‘sweet’ FU: 0.007, 95% CI: −0.077, 0.092; p=0.864; - ‘Processed’ v. ‘healthy’ FU: 0.001, 95% CI: −0.037, 0.038; p=0.982; - ‘Sweet’ v. ‘healthy’ FU: 0.019, 95% CI: −0.004, 0.081; p=0.539; FFMIzΔ; - ‘Processed’ v. ‘Healthy’ ref, T0: −0.004, 95% CI: −0.065, 0.056; p=0.893; - ‘Sweet’ v. ‘Healthy’ ref, T0: 0.013, 95% CI: −0.066, 0.091; p=0.752; - ‘Processed’ v. ‘processed’ FU: −0.043, 95% CI: −0.119, 0.032; p=0.262; - ‘Sweet’ v. ‘processed’ FU: −0.030, 95% CI: −0.184, 0.125; p=0.707; - ‘Healthy’ v. ‘processed’ FU: −0.038, 95% CI: −0.181,0.105; p=0.601; - ‘Processed’ v. ‘sweet’ FU: −0.011, 95% CI: −0.123, 0.100; p=0.84; - ‘Sweet’ v. ‘sweet’ FU: 0.007, 95% CI: −0.089, 0.104; p=0.882; - ‘Healthy’ v. ‘sweet’ FU: −0.073, 95% CI: −0.240, 0.093; p=0.385; - ‘Processed’ v. ‘healthy’ FU: 0.011, 95% CI: −0.064, 0.085; p=0.78; - ‘Sweet’ v. ‘healthy’ FU: 0.006, 95% CI: −0.115, 0.128; p=0.919; WCzΔ; - ‘Processed’ v. ‘Healthy’ ref, T0: 0.079, 95% CI: 0.022, 0.135; p=0.006; - ‘Sweet’ v. ‘Healthy’ ref, T0: 0.078, 95% CI: 0.006, 0.151; p=0.034; - ‘Processed’ v. ‘processed’ FU: 0.071, 95% CI: 0.001, 0.141; p=0.046; - ‘Sweet’ v. ‘processed’ FU: −0.015, 95% CI: −0.159, 0.129; p=0.842; - ‘Healthy’ v. ‘processed’ FU: 0.019, 95% CI: −0.113, 0.151; p=0.774; - ‘Processed’ v. ‘sweet’ FU: 0.172, 95% CI: 0.069, 0.275; p=0.001; - ‘Sweet’ v. ‘sweet’ FU: 0.127, 95% CI: 0.038, 0.216; p=0.005; - ‘Healthy’ v. ‘sweet’ FU: 0, 95% CI: −0.158, 0.158; p=0.998; - ‘Processed’ v. ‘healthy’ FU: 0.058, 95% CI: −0.011, 0.126; p=0.1; - ‘Sweet’ v. ‘healthy’ FU: 0.067, 95% CI: −0.045, 0.179; p=0.244 | - Did not account for: Race/ethnicity (Multi-country);; - Did not account for missing data; Funding: European Community’s Sixth RTD Framework Programme
Gasser, 2019 ^43^; Australia; Longitudinal Study of Australian Children (LSAC); Analytic N=2009 to 2014; Selection data: All participants enrolled in Australia’s Medicare database | Age at Dietary Pattern: 2 to 3y, B cohort; 4 to 5 y, K cohort by Wave (W); Dietary Score [Gasser 2017]: Positive: Vegetables; Fruits; Water; Milk products or alternatives; Negative: Fatty foods; Sweetened drinks; Sugary foods; ‘Healthy DP’: Positive: fresh fruit, cooked vegetables and raw vegetables or salad in all waves; water in most waves; dairy products and bread/toast in a few waves; ‘Unhealthy DP’: Positive: savoury snacks and sweetened drinks in all waves; meat pies, hamburgers, hot dogs, sausages or sausage rolls, hot chips and fruit juice in most waves; sugary foods, diet drinks, energy drinks, coffee and soya milk products mainly in the later waves; Negative: water in six of the eleven waves; Method: Index/Score and Factor/Cluster Analysis | Results at age(s) 14 to 15y; Dietary Score & BMIz, B cohort; - W2, β: 0.01, 95% CI: −0.03, 0.04; p-trend=0.7; - W3, β: −0.02, 95% CI: −0.05, 0.02; p-trend=0.34; - W4, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.57; - W5, β: −0.03, 95% CI: −0.06, 0.01; p-trend=0.17; Healthy DP & BMIz, B cohort; - W2, β: 0.01, 95% CI: −0.02, 0.05 ; p-trend=0.41; - W3, β: 0.02, 95% CI: −0.02, 0.05; p-trend=0.35; - W4, β: 0.01, 95% CI: −0.02, 0.05; p-trend=0.53; - W5, β: −0.03, 95% CI: −0.07, 0.02; p-trend=0.22; Unhealthy DP & BMIz, B cohort; - W2, β: 0.02, 95% CI: −0.03, 0.06; p-trend=0.46; - W3, β: 0.01, 95% CI: −0.03, 0.05; p-trend=0.54; - W4, β: 0.02, 95% CI: −0.01,0.05; p-trend=0.24; - W5, β: 0.01, 95% CI: −0.02, 0.05; p-trend=0.37; Dietary Score & Wt: Ht ratio, B cohort; - W2, β: 0.00, 95% CI: −0.03, 0.03; p-trend=0.90; - W3, β: −0.02, 95% CI: −0.06, 0.01; p-trend=0.21; - W4, β: −0.03, 95% CI: −0.06, 0.00; p-trend=0.06; - W5, β: −0.04, 95% CI: −0.07, 0.00; p-trend=0.05; Healthy DP & Wt: Ht ratio, B cohort; - W2, β: 0.01, 95% CI: −0.02, 0.04; p-trend=0.45; - W3, β: 0.00, 95% CI: −0.03, 0.03; p-trend=0.76; - W4, β: −0.03, 95% CI: −0.06, 0.01; p-trend=0.10; - W5, β: −0.05, 95% CI: −0.08, −0.01; p-trend=0.007; Unhealthy DP & Wt: Ht ratio, B cohort; - W2, β: 0.01, 95% CI: −0.03, 0.05; p-trend=0.62; - W3, β: 0.04, 95% CI: 0.00, 0.07; p-trend=0.03; - W4, β: 0.03, 95% CI: 0.00, 0.06; p-trend=0.03; - W5, β: 0.04, 95% CI: 0.00, 0.07; p-trend=0.03; Dietary Score & BMIz, K cohort; - W2, β: 0.01, 95% CI: −0.02, 0.04; p-trend=0.55; - W3, β: 0.00, 95% CI: −0.03, 0.03; p-trend=0.84; - W4, β: 0.00, 95% CI: −0.02, 0.03; p-trend=0.83; - W5, β: 0.02, 95% CI: −0.02, 0.07; p-trend=0.36; Healthy DP & zBMI, K cohort; - W2, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.47; - W3, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.42; - W4, β: 0.01, 95% CI: −0.02, 0.03; p-trend=0.52; - W5, β: 0.01, 95% CI: −0.03, 0.04; p-trend=0.73; Unhealthy DP & zBMI, K cohort; - W2, β: 0.00, 95% CI: −0.03, 0.03; p-trend=0.93; - W3, β: 0.01, 95% CI: −0.02, 0.04; p-trend=0.61; - W4, β: 0.00, 95% CI: −0.03, 0.03; p-trend=0.88; - W5, β: 0.00, 95% CI: −0.05, 0.04; p-trend=0.94; Dietary Score & Weight: Ht ratio, K cohort; - W2, β: −0.01, 95% CI: −0.05, 0.02; p-trend=0.45; - W3, β: −0.03, 95% CI: −0.07, 0.01; p-trend=0.12; - W4, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.58; - W5, β: −0.03, 95% CI: −0.07, 0.01; p-trend=0.16; Healthy DP & Weight: Ht ratio, K cohort; - W2, β: −0.01, 95% CI: −0.04, 0.02; p-trend=0.47; - W3, β: −0.02, 95% CI: −0.06, 0.02; p-trend=0.40; - W4, β: −0.03, 95% CI: −0.06, −0.00; p-trend=0.03; - W5, β: −0.05, 95% CI: −0.09, −0.00; p-trend=0.03; Unhealthy DP & Weight: Ht ratio, K cohort; - W2, β: 0.03, 95% CI: −0.01, 0.07; p-trend=0.18; - W3, β: 0.04, 95% CI: −0.00, 0.08; p-trend=0.07; - W4, β: −0.03, 95% CI: −0.07, −0.00; p-trend=0.03; - W5, β: 0.00, 95% CI: −0.03, 0.04; p-trend=0.86 | - Did not account for: n/a (all accounted for); - Derived dietary pattern scores for each child at each wave (0–1y B-Cohort; 4–5y K Cohort);; Funding: Department of Social Services, Australian Institute of Family Studies, Australian Bureau of Statistics
González, 2023 ^44^; Brazil; Uruguay; ENDIS & 2015-Pelotas-Birth Cohort; Analytic N=6468; 2550 (ENDIS), 3918 (Pelotas); Selection data: Included those from ENDIS, who were <4 y at baseline; children with data on dietary intake & measured height/weight; Pelotas: children recruited at birth; included those with two BMI measurements | Age at Dietary Pattern: 2y (~25mo); [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]): Cookies; Packaged dairy deserts; Sweetened Drinks; Cookies; Processed Meat products; Method: Index/Score Analysis: UP, Nova | Results at age(s) 4y (~48mo):; Risk of Obesity: UPF (baseline and current) & Incident Ob, RR: 1.02, 95% CI: 0.93, 1.12; p=0.680 | - Did not account for: Physical activity, Race/Ethnicity (‘Latin-American’); - Diet assessed once via 24h recall (wave 1 ENDIS) or FFQ (wave 2 ENDIS, Pelotas); Misclassification possible due to different diet aassessment methods between waves & cohorts and UPF intake based on FFQ; Funding: National Agency of Investigation and Innovation; Wellcome Trust; Conselho Nacional de Desenvolvimento Cienti’fico e Tecnolo’gico-Brazil; Fundação de Amparo a Pesquisa do Estado do Rio Grande do Sul; Children’s Pastorate
Heerman, 2023 ^45^; United States; Cohort from the GROW RCT; Analytic N=595; Selection data: Enrolled parent-child pairs qualified for at least one under-served population service (e.g., WIC), with normal to overweight/obesity (BMI b/n 50th and 95th %tile); spoke English/Spanish; telephone access; free of medical conditions precluding physical activity; lived/worked outside 5-mile radius of study centers | Age at Dietary Pattern: 4.3y, mean; 3y to 5y; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]), High (1300 kcal) vs. Low (300 kcal) e.g. Soft drinks; sweet or savoury packaged snacks; ice cream, chocolate, candies; massproduced packaged breads and buns; margarines and spreads; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; flavoured and/or artificial sweetened yoghurt; Method: Index/Score Analysis | Results at age(s) ~ 6 to 8y (36 mos FU); High v. low UPF & zBMI; - Only 3y olds: 1.2, 95% CI: 0.5, 1.9; p<0.001; - Only 4y olds: 0.6, 95% CI: 0.2, 1.0; p=0.007; - Only 5y olds: −0.1, 95% CI: −0.6, 0.4; p=0.7; - In all, mean age 4.3y: 0.4, 95% CI: −0.02, 0.7; p=0.07 | - Did not account for: Anthropometry at baseline (tested BMIz);; - Diet assessed at baseline only via 24-h-recall; mean daily calories from UPF in sample >60%; Funding: NHLBI
Hu, 2016 ^46^; United States; Project EAT; Analytic N=2656; Selection data: Excluded those with missing data | Age at Dietary Pattern: 15 y; [underlined: a priori diet quality score, APQDS], pediatric [Hu, 2016]: Positive: Green Vegetables, Tomato, Yellow Vegetables; Legumes; Fruit; Nuts; Whole Grains; Fish; Poultry; Low-Fat Dairy; Oil; Chocolate, Tea, Coffee; Negative: Fried potatoes; Red Meat, Liver, Processed Meat; Whole-Fat Dairy; Desserts; Soft drinks; Butter; Fried Foods; Sauces; Salty Snacks; Neutral: Other vegetables; Potatoes; Fruit Juices; Refined Grains; Seafood; Eggs; Margarine; Diet soft drinks; Method: Index/Score Analysis | Results at age(s) age ~15–25y; F/U: 5y, 10y;; APDQS and:; - BMI 5y f/u: −0.23, 95 % CI: −0.36,−0.11; p<0.001; - BMI 10y f/u: −0.47, 95 % CI: −0.72,−0.22; p<0.001; - Weight 5y f/u: −0.8, 95 % CI: −1.2, −0.4; p<0.001; - Weight 10y f/u:−1.5, 95 % CI: −2.3,−0.7; p<0.001; ΔAPDQS and:; - BMI, age 15–20y: −0.33, 95 % CI: −0.56, −0.10; p=0.005; - BMI, age 20–25y: −0.62, 95 % CI: −0.82, −0.41; p<.001; - BMI, age 15–25y: −0.53, 95 % CI: −0.69, −0.36; p<.001; - Weight, age 15–20y: −1.8, 95 % CI: −2.5,−1.1; p<0.001; - Weight, age 20–25y: −1.7, 95 % CI: −2.3,−1.1; p<0.0 | - Did not account for: n/a (all accounted for); - Self-reported outcome data; Did not account for missing data; Funding: National Heart, Lung, and Blood Institute; National Institute on Aging; NIH
Johnson, 2008 ^47^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=521 (DP age 5y); 628 (DP age 7y); Selection data: Excluded those with incomplete data | Age at Dietary Pattern: 5y; 7y; DP age 5y (top 10 components in rank): Positive for low-fiber bread; crisps and savory snacks; chocolate and confectionery; high-fat milk and cream; cheese and cheese dishes; Negative for fresh fruit; vegetables; potatoes boiled or baked; high-fiber bread; high-fiber breakfast cereals; DP age 7y (top 10 components in rank): Positive for crisps and savory snacks; chocolate and confectionery; low-fiber bread; biscuits and cakes; processed meat; Negative for fresh fruit; vegetables; high-fiber breakfast cereals; potatoes boiled or baked; high-fiber bread; Method: RRR | Results at age(s) 9y:; DP age 5y and:; - OW/Ob % Q1, 10; Q2, 12; Q3, 20; Q4, 20; Q5, 19; p=0.28; - BMI; ○ Q1, 16.8, 95% CI: 15.8, 18.5; ○ Q2, 16.5, 95% CI: 15.8, 19.4; ○ Q3, 17.1, 95% CI: 15.9, 19.3; ○ Q4, 17.3, 95% CI: 15.6, 19.2; ○ Q5, 17.1, 95% CI: 15.7, 19.1; ○ p=0.63; - Excess adiposity, per quintile: OR: 1.26, 95% CI: 1.03, 1.57; Q1, 13; Q2, 21; Q3, 20; Q4, 22; Q5, 22; p=0.13; - FM, per-SD: B: 0.14, 95% CI: −0.15, 0.45, p=0.34; ○ Q1, 6.5, 95% CI: 4.6, 9.8; ○ Q2, 6.3, 95% CI: 5.2, 11.1; ○ Q3, 8.4, 95% CI: 4.7, 11.3; ○ Q4, 7.4, 95% CI: 5.3, 10.9; ○ Q5, 7.5, 95% CI: 4.2, 10.0; ○ p=0.32; - FMI; ○ Q1, 0.98, 95% CI: 0.72, 1.41; ○ Q2, 0.99, 95% CI: 0.70, 1.62; ○ Q3, 1.04, 95% CI: 0.73, 1.56; ○ Q4, 1.07, 95% CI: 0.78, 1.60; ○ Q5, 1.10, 95% CI: 0.69, 1.58; ○ p=0.24; - BF%; ○ Q1, 20.0, 95% CI: 15.1,26.7; ○ Q2, 20.8, 95% CI: 14.7, 29.3; ○ Q3, 23.2, 95% CI: 15.9, 29.2; ○ Q4, 23.5, 95% CI: 17.7, 28.6; ○ Q5, 22.2, 95% CI: 15.0, 27.9; ○ p=0.20; DP age 7y and:; - OW/Ob %: Q1, 16; Q2, 18; Q3, 20; Q4, 23; Q5, 22; p=0.16; - Excess adiposity, per quintile: OR: 1.43, 95% CI: 1.18, 1.73; Q1, 13; Q2, 18; Q3, 20; Q4, 26; Q5, 23; p=0.01; - BMI; ○ Q1, 17.1, 95% CI: 15.8, 18.7; ○ Q2, 16.8, 95% CI: 15.8, 19.1; ○ Q3, 17.3, 95% CI: 15.8, 19.0; ○ Q4, 17.1, 95% CI: 15.7, 19.5; ○ Q5, 17.3, 95% CI: 15.8, 19.5; ○ p=0.35; - FM, per-SD: B: 0.23, 95% CI: 0.002, 0.47, p=0.04; ○ Q1,7.3, 95% CI: 4.6, 10.3; ○ Q2, 7.1, 95% CI: 5.2, 10.4; ○ Q3, 7.2, 95% CI: 4.5, 10.9; ○ Q4, 7.8, 95% CI: 4.6, 11.1; ○ Q5, 7.7, 95% CI: 5.1, 11.4; ○ p=0.40; - FMI; ○ Q1, 1.03, 95% CI: 0.70, 1.42; ○ Q2, 1.01, 95% CI: 0.77, 1.54; ○ Q3, 1.00, 95% CI: 0.72, 1.62; ○ Q4, 1.11, 95% CI: 0.76, 1.71; ○ Q5, 1.17, 95% CI: 0.80, 1.61; ○ p=0.04; - BF%; ○ Q1, 22.5, 95% CI: 15.3, 28.0; ○ Q2, 21.9, 95% CI: 16.9, 28.9; ○ Q3, 22.0, 95% CI: 15.0, 29.0; ○ Q4, 23.9, 95% CI: 15.4, 30.0; ○ Q5, 23.6, 95% CI: 17.1, 30.5; ○ p=0.18 | - Did not account for: Race/Ethnicity (UK birth-cohort), Physical activity,; - Diet assessed by parent using 3d unweighed food records at age 5y and 7y; Funding: Medical Research Council (MRC) Human Nutrition Research; the Unit of Paediatric and Perinatal Epidemiology, Department of Social Medicine, University of Bristol
Krijger, 2021 ^48^; Netherlands; Amsterdam Born Children and their Development (ABCD); Analytic N=869; Selection data: Excluded those with missing data; congenital CVD; used drugs intervening with CVD factors | Age at Dietary Pattern: 5 to 6y; DASH score [Fung, 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; CDQS [van der Velde, 2019]: Positive: fruits, vegetables, whole grains, fish, legumes, nuts, dairy, oils and soft liquid fats. Negative: sugar-containing beverages and processed meat; Method: Index/Score Analysis | Results at age(s) 11 to 12y:; DASH & OW: OR: 0.87, 95% CI: 0.73, 1.05; p = 0.159; CDQS & OW: OR: 0.86, 95% CI: 0.72, 1.04; p = 0.113; DASH & BMI; - Q1: 18.00 (0.14); - Q2: 17.96 (0.14); - Q3: 17.79 (0.16); - Q4: 17.61 (0.15); - Q5: 17.65 (0.17); - p = 0.016; CDQS & BMI; - Q1: 18.12 (0.15); - Q2: 17.77 (0.15); - Q3: 17.77 (0.15); - Q4: 17.85 (0.14); - Q5: 17.56 (0.16); - p = 0.036; DASH & WC; - Q1: 63.6 (0.4); - Q2: 63.5 (0.4); - Q3: 62.9 (0.4); - Q4: 62.7 (0.4); - Q5: 62.6 (0.5); - p = 0.028; CDQS & WC; - Q1: 63.7 (0.4); - Q2: 63.0 (0.4); - Q3: 63.4 (0.4); - Q4: 62.8 (0.4); - Q5: 62.7 (0.5); - p = 0.066 | - Did not account for: Race/Ethnicity (75% Dutch); - Sensitivity analyses: Excluding EI = diet and TG, NS for DASH (p = 0.069) & CDQS (p = 0.096); Inverse: CDQS & WC (p = 0.033) and DBP (p = 0.042).; - Excluding maternal ed. = NS for DASH; Inverse: CDQS & WC (p = 0.013) and DBP (0.031); Funding: Netherlands Organization for Health Research and Development, The Dutch Heart Foundation and Sarphati Amsterdam.
Lioret, 2014 ^50^; Australia; Resilience for Eating and Activity Despite Inequality (READI); Analytic N=216; Selection data: Enrolled only those living in socioeconomically-disadvantaged areas; Excluded those with missing data/LFU | Age at Dietary Pattern: 5 to 12y, mean 9.1y; Dietary Guideline Index for Children and Adolescents (DGI-CA): Fruit/100% fruit juice, vegetables and legumes, breads and cereals, wholegrain bread relative to total, meat and alternatives (excluding processed meat); dairy products: reduced- or low-fat dairy, water as a beverage, healthy fats: total fats, <3/d ‘extra foods’; Method: Index/Score Analysis | Results at age(s) F/U: 3y (age ~8 to 15y, ~12):; DGI-CA at T1 & zBMI at T2: 0.004, 95% CI: −0.003; 0.01; p=0.28; - Larger decrease in DQI, ref 0; - Smaller decreasei in DQI, −0.09, 95% CI: −0.24; 0.07; - Increase in DQI, −0.10, 95% CI: −0.27; 0.07; - P-trend=0.26; Effects were unchanged when stratified by age, sex, maternal education, or PA | - Did not account for: Race/Ethnicity; - Diet assessed at T1 and T2 with FFQ and validated index; Funding: National Health and Medical Research Council
Luque, 2021 ^51^; Germany, Belgium, Italy, Poland, and Spain; CHildhood Obesity Project (EU CHOP) trial; Analytic N=399; Selection data: Excluded those with incomplete diet/anthropometry data; moved from study region; illness or medication interfering with growth; lost contact; refusal | Age at Dietary Pattern: 2 y; 8y; ‘Core Foods Pattern’: Higher intakes of fruit, vegetables, potatoes, fish, white and red meat, and olive oil; ‘Poor-Quality Fats and Sugars’: Positively associated with intakes of potatoes, soft cheese, saturated spreads, fruit juices, and teas and negatively associated with intakes of fish and olive oil; ‘Protein Sources’: Vegetables, potatoes, white meat, red meat, processed fish, eggs, chips and snacks, flavored milk; Method: Factor/Cluster Analysis | Results at age(s) 8y:; - Core’: β: 0.21, 95% CI: 0.06, 0.35; p=0.006; - ‘Protein’: β: 0.13, 95% CI: −0.04, 0.30; p=0.131; - ‘Fats and Sugars’: β: −0.10, 95% CI: −0.27, 0.07; p=0.230 | - Did not account for: Race/Ethnicity, Physical activity; - Diet assessed at age 2y and 8y; Correlated intakes between 2y & 8y; Funding: 5th–7th Framework Program, European Union’s Horizon 2020 research and innovation programe
Marinho, 2022 ^52^; Portugal; Generation XXI; Analytic N=3575; Selection data: Excluded those that were pre-term children, children with dz influencing dietary intake and other congenital anomalies, children with characteristics that influence cognitive assessment, and missing data | Age at Dietary Pattern: 4y; ‘Energy-dense foods’ (EDF): high intakes of sweets, sugar-sweetened beverages, savory pastry, and processed meat.; ‘Snacking’: lower in foods usually consumed at lunch and dinner (e.g., vegetables on a plate, fish, meat, rice/pasta/potatoes), higher in intermediate foods typically eaten at snacking occasions; ‘Healthier’: higher consumption of fruit, vegetables, vegetable soup, and fish, with a lower consumption of EDF; Method: Latent Class Analysis | Results at age(s) 10y:; Mediation Analysis, of; ‘EDF’ – WWr; - Full Scale IQ: β: 0.032, 95% CI: −0.015, 0.082; - Performance IQ: β: 0.032, 95% CI: −0.017, 0.079; - Verbal IQ: β: 0.032, 95% CI: −0.017, 0.087; - Processing Speed IQ: β: 0.032, 95% CI: −0.021, 0.092; ‘Snacking’- WWr; - Full Scale IQ: β: 0.054, 95% CI: −0.005, 0.116; - Performance IQ: β: 0.054, 95% CI: −0.006, 0.119; - Verbal IQ: β: 0.054, 95% CI: −0.012, 0.119; - Processing Speed IQ: β: 0.054, 95% CI: −0.012, 0.113 | - Did not account for: Anthropometry at baseline, Age, Race/Ethnicity (100% Portuguese birth cohort); - Indirectly designed for mediation analysis on IQ; Funding: Health Operational Programme Saúde XXI, Community Support Framework III; Regional Department of Ministry of Health, Calouste Gulbenkian Foundation, by FEDER Operational Programme Factors of Competitiveness, Epidemiology Research Unit
Marks, 2015 ^53^; Australia; n/a; Analytic N=243; Selection data: Enrolled schools from bottom-SES strata | Age at Dietary Pattern: 11 to 13y, mean 12.2y; Non-core food score [Marks, 2015]: Positive: potato chips or a similar snack; chocolate; lollies (candy); muesli or fruit bars; savory biscuits; sweet biscuits; ice cream; hot chips (french fries); pies, pasties, or sausage rolls; hot dogs; pizza; Method: Index/Score Analysis | Results at age(s) mean, 12.7y (F/U 1y):; Non-core food & OW/Ob Mean difference: −0.6, 95% CI: −1.7 to 0.5; p=0.26 | - Did not account for: Anthropometry at baseline (within outcome), Physical activity, SEP all from bottom 2 SES strata); - Indirectly designed for obesity-related behaviors and change of school (not DP); Funding: Windermere Foundation
Martin-Calvo, 2016 ^54^; United States; Growing Up Today Study 2; Analytic N=10918; Selection data: Excluded those with missing data | Age at Dietary Pattern: 8 to 15 y; modified KIDMED, m-KIDMED [Serra-Majem, 2004]: Positive: Fruit or fruit juice, vegetables, fish, legumes, modified cereals/bread, nuts, olive oil, reduced- or low-fat dairy, yogurt/cheese; specified frequency or amounts/d/wk; Negative: fast food >1/wk, skipping breakfast, commercial bakery as breakfast, candies/sweets ≥ 1/d; Method: Index/Score Analysis | Results at age(s) F/U over 7y, ~ age 15 to 23y; Δ BMI after 7y f/u; - Q1, ref, 0; - Q2, 0.01, 95% CI: −0.09, 0.11; p=−0.89; - Q3, −0.09, 95% CI: −0.17, −0.00; p=0.05; - Q4, −0.11, 95% CI: −0.19, −0.03; p=0.005; - p-trend=0.11 | - Did not account for: Race/ethnicity, SEP; - Self-reported outcome data; Did not account for missing data; Funding: Breast Cancer Research Foundation; NIH
McCourt, 2014 ^55^; Ireland; Young Hearts I & III; Analytic N=487; Selection data: NR | Age at Dietary Pattern: 12 to 15y; Mediterranean Diet Score (MDS) [Trichopolou 2003]: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Method: Index/Score Analysis | Results at age(s) 20 to 25y:; MDS & BMI, mean [SD]; - Least-least adherent: 23.9[3.9]; - Least-most adherent: 23.3[3.3]; - Most-least adherent: 24.4[3.7]; - Most-most adherent: 24.5[3.9]; - p=0.16; ΔMDS & ΔBMI YH1-YH3, mean [SD]; - Least-least adherent: 4 [3]; - Least-most adherent: 3.8 [2.6]; - Most-least adherent: 3.7 [3]; - Most-most adherent: 3.5 [3]; - p=0.688; MDS & WC, mean [SD]; - Least-least adherent: 78.5[10.8]; - Least-most adherent: 77.1[9.4]; - Most-least adherent: 79.9[10.1]; - Most-most adherent: 80.4[10.8]; - p=0.218 | - Did not account for: Race/Ethnicity (Irish); - Diet assessed with 7d diet Hx at multiple time points; Funding: YHI: Northern Ireland Chest, Heart and Stroke Association and the Department of Health and Social Services; YHIII: Wellcome Trust, British Heart Foundation.
Nguyen, 2020 ^10^; Netherlands; Generation R Study; Analytic N=3991; Selection data: Enrolled participants at birth; Excluded those with missing FFQ or outcome data | Age at Dietary Pattern: 8 y; Children’s Diet Quality (DQ) Score (CDQS) [van der Velde, 2018]: Positive: Vegetables; Fruit; Nuts; Legumes; Whole grains; Dairy; Fish; Oils and fats; Negative: High-fat and processed meats; Sugar-containing beverages; Method: Index/Score Analysis | Results at age(s) 10y:; - BMI, β: 0.02, 95% CI: −0.003, 0.04; When stratified by sex, results were only significant in girls; - FMI, β: −0.001, 95% CI: −0.03, 0.02; - FFMI, β: 0.06, 95% CI: 0.04, 0.09; - %BF, β: −0.02, 95% CI: −0.04, 0.01; Similar results when stratified by sex; - Weight, β: 0.04, 95% CI: 0.01, 0.06; When stratified by sex, results were only significant in girls | - Did not account for: Anthropometry at baseline (Excluding those with baseline Ob/OW yielded similar results); - Previously reported results with outcomes at age 6 y; Excluding children with baseline Ob/OW yielded similar results; Excluding individual DQ components yielded similar results; Analyses of only Dutch children yielded similar results; Effect estimates with DQ at 8 y were generally higher in girls compared to boys; Funding: Erasmus Medical Center (EMC) Erasmus University Rotterdam(EUR); the Netherlands Organization for Health Research and Development
Notario-Barandiaran, 2020 ^56^; Spain; INMA; Analytic N=1527; Selection data: Excluded those without data on BMI, diet, and variables of interest at age 4 and/or age 8 y | Age at Dietary Pattern: 4y; relative Mediterranean Diet Score (rMED) [Buckland 2009]: Positive: Vegetables (not potatoes); Legumes; Fruit, Nuts, and Seeds (not juice); Whole Grains, Refined Flour, Pasta, Rice, Bread, Grains; Fish; Olive Oil. Negative: Total and Processed Meat. (excluded alcohol due to age group); Method: Index/Score Analysis | Results at age(s) 8y:; OW, low as ref; - Medium, PR: 0.79, 95% CI: 0.55, 1.13; p-trend=0.200; - High, PR: 0.38, 95% CI: 0.21,0.67; p-trend=0.001; - Per 2 pt, PR: 0.88, 95% CI: 0.78, 1.00; p-trend=0.047; Ob, low as ref; - Medium, PR: 0.92, 95% CI: 0.53, 1.59; p-trend=0.776; - High, PR: 0.16, 95% CI: 0.05, 0.53; p-trend=0.002; - Per 2 pt, PR: 0.80, 95% CI: 0.66, 0.97; p-trend= 0.026; Abdominal obesity, low as ref; - Medium, PR: 1.01, 95% CI: 0.58, 1.73; p-trend=0.982; - High, PR: 0.30, 95% CI: 0.12, 0.73; p-trend=0.008; - Per 2 pt, PR: 0.82, 95% CI: 0.68, 0.99; p-trend=0.041 | - Did not account for: Anthropometry (adjusted for SGA); Race/Ethnicity, Physical activity; - Adjusted for SGA by Weight, but not anthropometry at baseline; Diet assessed with validated FFQ at age 4y only (baseline); Funding: Instituto de Salud; Carlos III, Spanish Ministry of Health; University of Oviedo, Conselleria de Sanitat Generalitat Valenciana, Generalitat de Catalunya-CIRIT 1999SGR; Generalitat de Catalunya-AGAUR; Department of Health of the Basque Government; the Pro
Oellingrath, 2017 ^57^; Norway; n/a; Analytic N=393; Selection data: NR | Age at Dietary Pattern: 12 to 13y, mean 12.7; ‘junk convenient’, characterised by high-energy processed fast foods, refined grains, cakes and sweets;; ‘varied Norwegian’, characterised by food items typical of a traditional Norwegian diet, including fruits and vegetables, brown bread, fish, water and regular breakfast and lunch, close to official nutritional guidelines;; ‘snacking’, characterised by sugar-rich snack items and drinks, low intake of vegetables and brown bread, low frequency of breakfast and dinner and high frequency of eating between meals;; ‘dieting’, characterised by foods and drinks often associated with weight control, like artificial sweetened drinks and other ‘light’ products; Method: Factor/Cluster Analysis | Results at age(s): ~ 15 to 16y, F/U 3y; OW at 10th grade, in those “normal weight” at baseline (T1 ref); - ‘Junk Convenient’, T2+T3, OR: 0.9, 95% CI: 0.4, 2.3; - ‘Norwegian’, T2+T3, OR: 0.8, 95% CI: 0.3, 1.9; - ‘Snacking’, T2+T3, OR: 0.8, 95% CI: 0.3, 2.0; - ‘Dieting’, T2+T3, OR: 1, 95% CI: 0.4, 2.5; OW at 10th grade, in those “OW” at baseline (T1 ref); - ‘Junk Convenient, T2+T3, OR: 2.2, 95% CI: 0.6, 8.6; - ‘Norwegian’, T2+T3, OR: 0.5, 95% CI: 0.1, 2.0; - ‘Snacking’, T2+T3, OR: 1.4, 95% CI: 0.4, 5.1; - ‘Dieting’, T2+T3, OR: 1, 95% CI: 0.2, 5.1 | - Did not account for: Race/Ethnicity (Norwegian); - Diet assessed with valid FFQ at 7th and 10th grade; DP combined with PA reduced odds of OW, but only in those already OW; Funding: Research Council of Norway and the Public Health Programme for Telemark
Okubo, 2015 ^11^; United Kingdom; Southampton Women’s Survey; Analytic N=1018; Selection data: Excluded those with missing data | Age at Dietary Pattern: 3y; ‘Prudent’ (DQ score): Fish and shellfish, vegetables (salad, green, root other), other fruits; Method: Factor/Cluster Analysis | Results at age(s) 6y; OW/Ob: RR: 0.97, 95% CI: 0.89, 1.06; p-trend=0.55; BMIz at 6y; - T1, B: 0.07, 95% CI: −0.15, 0.29; - T2, B: 0.02, 95% CI: −0.18, 0.23; - T3, ref; - p=0.025; - per-unit, B: −0.06, 95% CI: −0.15, 0.04; FM at 6y; - T1, B: 0.23, 95% CI: 0.01, 0.45; - T2, B: 0.01, 95% CI: −0.20, 0.21; - T3, ref; - p=0.01; per-unit, B: −0.12, 95% CI: −0.22, −0.02 | - Did not account for: Anthropometry (adjusted for Ht), Race/ethnicity, SEP; Funding: Medical Research Council, the British Heart Foundation, Arthritis Research United Kingdom, the National Osteoporosis Society, the International Osteoporosis Foundation, the Cohen Trust, the National Institute for Health Research Southampton Biomedical Research
Pala, 2013 ^58^; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain; IDEFICS (Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS) study; Analytic N=9427; Selection data: Excluded those with missing data | Age at Dietary Pattern: 2 to 10 y; ‘Snacking’: Street foods (e.g., sandwiches), savory pastries, chocolate bars; ‘Sweet’: Chocolate spreads, biscuits and sweets/candy, fried meat, soft drinks; ‘Vegetables and Wholemeal’: Vegetables, fruits, wholemeal cereal products, unsweetened milk; ‘Protein and Water’: Fish, meat, eggs, water; Method: Factor/Cluster | Results at age(s) 4 to 12y; Risk OW/Ob; ‘Snacking’ T1, ref 1; - T2, OR: 1.09, 95% CI: 0.88, 1.35; - T3, OR: 1.18, 95% CI: 0.91, 1.52; p-trend=0.22; - per-unit, OR: 1.03, 95% CI: 0.97, 1.09; ‘Sweet and fat’ T1, ref 1; - T2, OR: 1.08, 95% CI: 0.88, 1.33; - T3, OR: 0.97, 95% CI: 0.77, 1.22; p-trend=0.74; - per-unit, OR: 1.01, 95% CI: 0.95, 1.07; ‘Vegetables and wholemeal’ T1, ref 1; - T2, OR: 0.76, 95% CI: 0.62, 0.94; - T3, OR: 0.69, 95% CI: 0.54, 0.88; p-trend=0.003; - per-unit, OR: 0.93, 95% CI: 0.87, 0.99; ‘Protein and water’ T1, ref 1; - T2, OR: 1, 95% CI: 0.80, 1.25; - T3, OR: 0.95, 95% CI: 0.74, 1.23; p-trend=0.59; - per-unit, OR: 1, 95% CI: 0.93, 1.06; Δ BMI after 2y f/u; - Snacking’; ○ T1, mean Δ: 0.73; ○ T2, mean Δ: 0.76; p=0.51; ○ T3, mean Δ: 0.78; p=0.35; ○ p-trend=0.36; - ‘Sweet and fat’; ○ T1, mean Δ: 0.73; ○ T2, mean Δ: 0.76; p=0.55; ○ T3, mean Δ: 0.78; p=0.26; ○ p-trend=0.26; - ‘Vegetables and wholemeal’; ○ T1, mean Δ: 0.80; ○ T2, mean Δ: 0.73; p=0.04; ○ T3, mean Δ: 0.74; p=0.11; ○ p-trend=0.18; - ‘Protein and water’; ○ T1, mean Δ: 0.73; ○ T2, mean Δ: 0.74; p=0.19; ○ T3, mean Δ: 0.80; p=0.16; ○ p-trend=0.11 | - Did not account for: Race/ethnicity (Country); - Diet measured once at baseline; Water intake was imputed; Did not account for missing data; Funding: European Community’s Sixth RTD Framework Programme
Pinto, 2021 ^60^; Portugal; Generation XXI; Analytic N=4698; Selection data: Excluded twins, no diet or other variables of interest, lack of f/up, incomplete data | Age at Dietary Pattern: 7 y; regression analysis (no label): yogurt, cheese, bread, cakes, carbonated soft drinks; ‘Western’: positively associated with sugary drinks, candies, sweets, and salty snacks; negatively associated with fishery, vegetable soup, and fruits; ‘DASH diet based’: positively associated with fruits and vegetables, fishery, and dairy; ‘energy-dense foods’: positively associated with ice cream, cheese, sausage, ham, bread, cakes, coffee, coke, carbonated and noncarbonated soft drinks; negatively associated with whole milk and vegetable soup; ‘fish based’: positively associated with fishery; negatively associated with more energy dense food; Method: Factor/Cluster | Results at age(s) 10y; zBMI; - regression analysis (no label): β=0.168, 95% CI: 0.088, 0.248; - ‘western’: β=0.023, 95% CI: 0.006, 0.040; - ‘DASH diet based’: β=0.004, 95% CI: −0.012, 0.021; - ‘energy-dense foods’: β=0.032, 95% CI: 0.017, 0.047; - ‘fish based’:β=−0.001, 95% CI: −0.012, 0.011 | - Did not account for: Race/Ethnicity (100% Portugese-birth cohort); - Effects remained unchanged in additional analyses by sex and energy intake; ‘energy-dense foods’ DP was more likely among children from younger and less educated mothers and/or children who were born heavier and did not practice regular PA at age 7y.; Funding: Generation XXI: Health Operational Programme Saúde XXI, Community Support Framework III, Regional Department of Ministry of Health; the study: FEDER Operational Programme Factors of Competitiveness Foundation for Science and Technology (Portuguese Ministry of Education and Science), Calouste Gulbenkian Foundation
Rashid, 2020 ^61^; Netherlands; Amsterdam Born Children and their Development (ABCD); Analytic N=1765; Selection data: Excluded those with multiple pregnancy, LFU, non-response; lack of or invalid FFQ; did not attend 10 y health check | Age at Dietary Pattern: 5 y; ‘Snacking’: Sweet and savory snacks, refined breakfast products, and low intakes of whole grain breakfast products; ‘Full-fat’: Full-fat spreads and pasta dishes and low intakes of low-fat spreads; ‘Meat’: Low and high fat meat, sauces and refined grain products for warm meals; ‘Healthy pattern’: Water and tea, vegetables, fish, and fruits; Method: Factor/Cluster | Results at age(s) 10y:; By Ethnicity; ‘Snacking’; ○ Dutch: β: −0.047, 95% CI: −0.102, 0.008; ○ African Sur: β: −0.096, 95% CI: −0.345, 0.152; ○ Turkish: β: 0.203, 95% CI: −0.209, 0.615; ○ Moroccan: β: −0.093, 95% CI: −0.356, 0.171; ○ Other: β: −0.025, 95% CI: −0.154, 0.104; ‘Full-fat’; ○ Dutch: β: −0.069, 95% CI: −0.114, −0.024; ○ African Sur: β: 0.150, 95% CI: −0.090, 0.390; ○ Turkish: β: −0.165, 95% CI: −0.486, 0.155; ○ Moroccan: β: 0.125, 95% CI: −0.168, 0.417; ○ Other: β: −0.130, 95% CI: −0.285, 0.025; ‘Meat’; ○ Dutch: β: 0.020, 95% CI: −0.027, 0.066; ○ African Sur: β: −0.033, 95%CI: −0.245, 0.180; ○ Turkish: β: 0.272, 95% CI: −0.091, 0.155; ○ Moroccan: β: 0.080, 95% CI: −0.163, 0.324; ○ Other: β: 0.030, 95% CI: −0.101, 0.161; ‘Healthy’; ○ Dutch: β: 0.092, 95% CI: 0.047, 0.137; ○ African Sur: β: −0.014, 95% CI: −0.264, 0.237; ○ Turkish: β: 0.221, 95% CI: −0.190, 0.632; ○ Moroccan: β: 0.259, 95% CI: 0.002, 0.516; ○ Other: β: 0.047, 95% CI: −0.122, 0.216; By SES; - Low/middle SES; ○ ‘Snacking’: β: 0.019, 95% CI: −0.071, 0.108; ○ ‘Full-fat’: β: −0.062, 95% CI: −0.147, 0.023; ○ ‘Meat’: β: 0.042, 95% CI: −0.045, 0.128; ○ ‘Healthy’: β: 0.094, 95% CI: 0.008, 0.179; - High SES:; ○ ‘Snacking’: β: −0.081, 95% CI: −0.136, −0.025; ○ ‘Full-fat’: β: −0.072, 95% CI: −0.119, −0.026; ○ ‘Meat’: β: 0.013, 95% CI: −0.033, 0.059; ○ ‘Healthy’: β: 0.096, 95% CI: 0.047, 0.143 | - Did not account for: Physical activity; - Diet assessed only at age 5y (baseline); FFQ validated for Dutch but not other ethnicities studied; Examined different ethnicities within a Dutch population; - Results were independent of energy intake; Sensitivity analyses were mainly NS with no clear pattern by BMI category; Funding: Netherlands Organisation for Scientific Research; ABCD study supported by Academic Medical Centre, The Netherlands and Public Health Service
Saldanha-Gomes, 2017 ^62^; France; EDEN; Analytic N=883; Selection data: Excluded those with multiple pregnancy, diabetes Hx, French illiteracy, plans to move | Age at Dietary Pattern: 2 y; ‘Guidelines’: high frequency of cooked vegetables, rice, fruits, raw vegetables, low fat fish, potatoes, ham, compotes, meat, and bread; ‘Processed, fast foods’: high freqency of French fries, processed meat, carbonated soft drinks, crisps, biscuits, pizzas, fruit juices, dairy puddings and ice cream, legumes, and bread; low in cooked vegetables; Method: Factor/Cluster - UP? | Results at age(s) 5y:; Processed, fast-food’; - ♂ BMI −0.04, 95% CI: −0.11, 0.04; P=0.364; - ♀ BMI 0.08, 95% CI: −0.01, 0.17; P=0.099; ‘Guidelines’; - ♂ BMI −0.01, 95% CI: −0.09, 0.07; P=0.81; - ♀ BMI −0.07, 95% CI: −0.16, 0.02; P=0.12; ‘Processed, fast-food’; - ♂ BF% 0.02, 95% CI: −0.20, 0.25; P=0.829; - ♀ BF% 0.19, 95% CI: −0.08, 0.46; P=0.176; ‘Guidelines’; - ♂ BF% 0.00, 95% CI: −0.22, 0.22; P=0.97; - ♀ BF% −0.21, 95% CI: −0.47, 0.06; P=0.12 | - Did not account for: Race/Ethnicity; - Diet assessed at age 2y only via FFQ; Complete-case analysis produced similar/consistent results as main findings; EDEN participants generally higher SEP than rest of France; Funding: Foundation for Medical Research, National Agency for Research, National Institute for Research in Public Health, French Ministry of Health, French Ministry of Research, INSERM Bone and Joint Diseases National Research, Human Nutrition National Research
Saldanha-Gomes, 2022 ^63^; France; EDEN; Analytic N=1138; Selection data: Excluded children who died, dropped out, 2y questionnaire not returned, age at adiposity rebound not calculable | Age at Dietary Pattern: 2 y; ‘Processed and fast foods’: high intakes of French fries, processed meat, carbonated soft drinks, crisps, biscuits, pizzas, fruit juices, dairy puddings and ice cream, legumes and bread and lower in cooked vegetables.; ‘Nutrient-dense foods’: high intake of cooked vegetables, rice, fruits, raw vegetables, low fat fish, potatoes, ham, compotes, meat and bread.; Method: Factor/Cluster | Results at age(s) 5.5y, mean; Adiposity rebound (AR) (dichotomous; 3.8y boys/3.6y girls); - ‘Processed and fast foods’: OR: 1.23, 95% CI: 1.00, 1.50; p=0.05; - ‘Nutrient-dense foods’: OR: 0.93, 95% CI: 0.76, 1.15; p=0.51; AR (continuous); - ‘Processed and fast foods’: β: −24, 95% CI: −55, 8); p=0.14; - ‘Nutrient-dense foods’: β: 12, 95% CI: −18, 42; p=0.43 | - Did not account for: Race/Ethnicity; - Diet assessed at age 2y only via FFQ; EDEN participants generally higher SEP than rest of France; Funding: Foundation for medical research, National Agency for Research, National Institute for Research in Public Health, French Ministry of Health, French Ministry of Research, INSERM Bone and Joint Disease National Research, Human Nutrition National Research Pro
Santos, 2019 ^15^; Brazil; Pelotas Birth Cohort Study; Analytic N=3374; Selection data: Excluded those missing BMI at 6 y or LFU | Age at Dietary Pattern: 2y, 4y; at 2 y; - ‘Milks’: positive for breast milk, negative for cow’s milk; - ‘Staple’: positive for rice and beans, negative for pasta; - ‘Beverages’: positive for juice, negative for water and tea; - ‘Snacks’: positive for coffee, bread, cookies, negative for yogurt; - ‘Meat and vegetables’: positive for meats, vegetables, legumes, potato and cassava, and fruits; at 4 y; - ‘Milks’: positive for cow’s milk and chocolate powder; - ‘Staple’: positive for rice, beans, and meat; - ‘Beverages’: positive for juice, negative for soft drinks; - ‘Snacks’: positive for coffee, bread and cookies, and water and tea, negative for yogurt and soft drinks; - ‘Treats’: positive for crisps, sweets, and chocolate; Method: Factor/Cluster | Results at age(s) 6y; Milks, 2y & zBMI, T1, β=1, ref; - T2, β= −0.03, 95% CI: −0.16, 0.09; - T3, β= 0.06, 95% CI: −0.08, 0.21; - p-trend = 0.451; Staple, 2y & zBMI, T1, β=1, ref; - T2, β= 0.09, 95% CI: −0.04, 0.22; - T3, β= 0.11, 95% CI: −0.02, 0.24; - p-trend = 0.085; Meat and vegetables, 2y & zBMI, T1, β=1, ref; - T2, β= 0.03, 95% CI: −0.10, 0.15; - T3, β= 0.07, 95% CI: −0.06, 0.20; - p-trend = 0.271; Beverages, 2y & zBMI, T1, β=1, ref; - T2, β= −0.03, 95% CI: −0.16, 0.09; - T3, β= −0.07, 95% CI: −0.19, 0.06; - p-trend = 0.306; Snacks, 2y & zBMI, T1, β=1, ref; - T2, β= −0.11, 95% CI: −0.24, 0.02; - T3, β= −0.08, 95% CI: −0.22, 0.05; - p-trend = 0.223; Milks, 4y & zBMI, T1, β=1, ref; - T2, β= 0.03, 95% CI: −0.10, 0.17; - T3, β= 0.03, 95% CI: −0.10, 0.16; - p-trend = 0.650; Staple, 4y & zBMI, T1, β=1, ref; - T2, β= −0.03, 95% CI: −0.16, 0.10; - T3, β= −0.03, 95% CI: −0.16, 0.10; - p-trend = 0.671; Treats, 4y & zBMI, T1, β=1, ref; - T2, β= −0.08, 95% CI: −0.21, 0.05; - T3, β= −0.03, 95% CI: −0.16, 0.09; - p-trend = 0.597; Beverages, 4y & zBMI, T1, β=1, ref; - T2, β= 0.05, 95% CI: −0.07, 0.18; - T3, β= −0.01, 95% CI: −0.15, 0.12; - p-trend = 0.846; Snacks, 4y & zBMI, T1, β=1, ref; - T2, p= −0.07, 95% CI: −0.20, 0.07; - T3, β= −0.17, 95% CI: −0.30, 0.03; - p-trend = 0.019; Milks, 2y & Corpulence, T1, β=1, ref; - T2, β= −0.02, 95% CI: −0.11, 0.07; - T3, β= 0.01, 95% CI: −0.09, 0.12; - p-trend = 0.832; Staple, 2y & Corpulence, T1, β=1, ref; - T2, β= 0.04, 95% CI: −0.05, 0.13; - T3, β= 0.09, 95% CI: −0.01, 0.18; - p-trend = 0.059; Meat and vegetables, 2y & Corpulence, T1, β=1, ref; - T2, β= 0.03, 95% CI: −0.06, 0.12; - T3, β= 0.08, 95% CI: −0.02, 0.17; - p-trend = 0.126; Beverages, 2y & Corpulence, T1, β=1, ref; - T2, β= −0.06, 95% CI: −0.15, 0.04; - T3, β= −0.03, 95% CI: −0.13, 0.06; - p-trend = 0.539; Snacks, 2y & Corpulence, T1, β=1, ref; - T2, β= −0.06, 95% CI: −0.15, 0.04; - T3, β= −0.05, 95% CI: −0.15, 0.05; - p-trend = 0.306; Milks, 4y & Corpulence, T1, β=1, ref; - T2, β= 0.04, 95% CI: −0.06, 0.13; - T3, β= 0.05, 95% CI: −0.04, 0.15; - p-trend = 0.286; Staple, 4y & Corpulence, T1, β=1, ref; - T2, β= −0.02, 95% CI: −0.08, 0.11; - T3, β= 0.04, 95% CI: −0.06, 0.14; - p-trend = 0.404; Treats, 4y & Corpulence, T1, β=1, ref; - T2, β= 0.00, 95% CI: −0.10, 0.09; - T3, β= −0.02, 95% CI: −0.11, 0.07; - p-trend = 0.669; Beverages, 4y & Corpulence, T1, β=1, ref; - T2, β= 0.03, 95% CI: −0.06, 0.13; - T3, β= 0.03, 95% CI: −0.07, 0.13; - p-trend = 0.537; Snacks, 4y & Corpulence, T1, β=1, ref; - T2, β= −0.07, 95% CI: −0.16, 0.03; - T3, β= −0.09, 95% CI: −0.19, 0.01; - p-trend = 0.077 | - Did not account for: Race/Ethnicity (adjusted skin color), Physical activity; - Corpulence included measures of body circumference (waist, hip, seat, chest, abdomen, knee, calf, and biceps circumferences), diameters (sagittal diameter, waist, abdomen width), and volumes (body volume and torso); Funding: Wellcome Trust, WHO, Brazilian National Research Council, Brazilian Ministry of Health, ‘Science without Borders’ Brazilian scheme
Setayeshgar, 2017 ^64^; Canada; QUebec Adipose and Lifestyle InvesTigation in Youth (QUALITY); Analytic N=546; Selection data: Enrolled those with one parent with Ob; Excluded those with DM, any serious illness/condition, on anti-HTN meds or steroids; or restricted diet | Age at Dietary Pattern: 8 to 10y; modified Diet Quality Index-International (DQI-I) [Kim, 2003]: m DQI score: Positive (Adequacy): Vegetable group; Fruit group; Grain group; Fiber; Protein; Iron; Calcium; Vitamin C; Negative: Total Fat, SFA, Cholesterol; Sodium; Empty-Energy Foods. Neutral: Carbohydrate: Protein: Fat Ratio; PUFA: MUFA: SFA ratio; Variety; Method: Index/Score Analysis | Results at age(s) ~ 10 to 12y; F/U: 2y; - DQI & BMI, β: −0.06, 95% CI: −0.26, 0.14; - DQI & FMI, β: −0.16, 95% CI: −0.33, 0.01; - DQI & BF%, β: −0.55*, 95% CI: −1.08, −0.02; p<0.05; - DQI & central FMI, β: −0.08, 95% CI: −0.17, −0.003; p<0.05; - DQI & central BF%, β: −0.28, 95% CI: −0.55, 0.0007 | - Did not account for: Race/Ethnicity (Caucasian), SEP (all higher SES); - Diet assessed using 3, 24h-recalls at baseline only; Funding: Canadian Institutes of Health Research; Heart and Stroke Foundation of Canada; Fonds de la Recherche en Santé du Québec
Shinsugi, 2020 ^65^; Japan; n/a; Analytic N=110; Selection data: Excluded those with missing data at baseline or follow-up; outlying data on the outcome variables; incorrect values of age and sex | Age at Dietary Pattern: 4.8y, mean; modified Japanese Food Guide [Kurotani 2016]: Positive: Vegetable Dishes; Fruit; Grain Dishes; Fish and Meat Dishes; White: Red Meat; Milk. Negative: Energy from Beverages & Snacks; Total Energy Intake; Method: Index/Score Analysis | Results at age(s): 5 to 7y; F/U: 1y; ΔBMI-for-age; - T1, β: 1, ref; - T2, β: 0.16, 95% CI: −0.29, 0.60; - T3, β: −0.14, 95% CI: −0.61, 0.33; ΔHt-for-age; - T1, β: 1, ref; - T2, β: −0.15, 95% CI: −0.50, 0.21; - T3, β: −0.06, 95% CI: −0.43, 0.30 | - Did not account for: Race/Ethnicity (Japanese public preschoolers); - Outcome from parent-reported height and weight; DQ based on guardian-reported dietary intake; Sample size <300; Funding: Japan Society for the Promotion of Science, Asahi Group Foundation
Siddiqui, 2022 ^66^; Netherlands; Generation R Study; Analytic N=3991; Selection data: Enrolled participants at birth; Excluded those with missing FFQ or outcome data | Age at Dietary Pattern: 8 y; Children’s Diet Quality (DQ) Score (CDQS) [van der Velde, 2018]: Positive: Vegetables; Fruit; Nuts; Whole Grains; Dairy Products; Fish; Oils and fats; Negative: Meat; Sugar-containing beverages;; Method: Index/Score Analysis | Results at age(s) 10y; - BF%, β: −0.03, 95% CI: −0.05, 0.001 | - Did not account for: Anthropometry (but analyses adjusting for weight/height yielded similar results); - Non-fasting blood samples (insulin, TG, and HDL); LDL cholesterol calculated according to the Friedewald formula; % BF results were not adjusted for anthropometry but additional analyses with Weight & Height showed similar results; Funding: Erasmus Medical Center (EMC), the Dutch Ministry of Health, Welfare, and Sports, and the Netherlands Organization for Health Research and Development
Sirkka, 2021 ^67^; Netherlands; GECKO Drenthe birth cohort; Analytic N=938; Selection data: Excluded those with incomplete dietary and covariate data; no BMI measurement age 3 to 10 y; LFU | Age at Dietary Pattern: 3 y; ‘Minimally processed’: high intakes of vegetables, sauces, rice/pasta, and savory dishes; ‘Ultra-processed’: high intakes of white bread, crisps, savory snacks, and SSB; low intakes of whole-grain bread; Method: Factor/Cluster- UP | Results at age(s) 10y; ‘Minimally processed’ & OW at 10y: OR: 1.03, 95% CI: 0.86, 1.24; p=0.74; ‘Ultra-processed food’ & OW at 10y: OR: 1.30, 95% CI: 1.08, 1.57; p=0.006 | - Did not account for: Physical activity; - Diet assessed by parent via FFQ at baseline only (age 3y); FFQ validated for children 4–6y; Funding: Unrestricted grant of Hutchison Whampoa Ltd., Hong Kong, and supported by the University of Groningen, Well Baby Clinic Foundation Icare, Noordlease, Paediatric Association Of The Netherlands, Youth Preventive Health Care Drenthe, and the European Union’s
Smith, 2014 ^68^; United Kingdom; Avon Longitudinal Study of Parents and Children (ALSPAC); Analytic N=3911; Selection data: Excluded those with missing data; other reasons NR | Age at Dietary Pattern: 9 y; ‘Health Aware’: Higher loadings for fruits and vegetables, high-fiber bread, pasta, cheese, and fish, lower loadings for chips (French fries), crisps (potato and corn snacks), processed meat, fizzy (carbonated) drinks; ‘Traditional’: Higher loadings for meat, roast potatoes, vegetables, batter and pastry products, low energy-density sauces (e.g. gravy, desserts); ‘Packed Lunch’: Higher loadings for low-fiber bread, margarine, cheese, cold meats, salty flavorings such as yeast extract, diet squash (dilutable soft drink); Method: Factor/cluster analysis | Results at age(s) 11y; In valid reporters, FM, ♂; - ‘Health aware’, 0.991, 95% CI: 0.978,1.005; - ‘Traditional’, 1.003, 95% CI: 0.990,1.016; - ‘Packed-lunch’, 0.989, 95% CI: 0.976,1.002; In valid reporters, FM, ♀; - Health aware’: 0.988, 95% CI: 0.976,1; - Traditional’: 0.992, 95% CI: 0.981,1 | - Did not account for: Race/ethnicity (97% White); - Diet assessed once each age time point; unclear timing of diet measurement in relation to outcomes; - Unclear if diet assessment methods were valid/reliable; - Did not account for missing data; Funding: The UK Medical Research Council, the Wellcome Trust and the University of Bristol; World Cancer Research Fund
Sorensen, 2021 ^69^; Norway; Norwegian Mother, Father and Child Cohort Study (MoBa); Analytic N=17513; Selection data: Excluded those with mothers with no available baseline socio-demographic, lifestyle and health related data; no maternal diet data during pregnancy; missing dietary data at child age 3 and/or 7 y | Age at Dietary Pattern: 3 y; modified MDS [Tognon 2014 modified Knoops 2004 modified Trichopolou 2003)]: Positive: Vegetables; Fruit; Cereals; Fish and Fish Products; MUFA+PUFA/SFA; Alcohol. Negative: Meat, Meat Products, and Eggs; Dairy Products; children’s Diet Quality Index (cDQI) [Huybrechts 2010]: Vegetables (no juices/soups); Fruit (no juices); Potatoes and grains; Bread and cereals; Milk products (milk, sugared milks, yoghurt, milk deserts, Ca+ soy drinks); Cheese; Meat, game, poultry, fish, and meat replacements; Restricted food groups: Beverages; Snacks (sweet, salty, chocolate, brioches, sweet desserts); Sugared drinks (tea, soft drinks); Fruit juice; Method: Index/Score Analysis | Results at age(s) 8y; modified MDS & OW, Low, OR: 1, ref High, OR: 0.98, 95% CI: 0.83, 1.16; DQI (DQ scale only) & Ob; - per-SD, OR: 0.886, 95% CI: 0.810, 0.969; - T1, OR: 1, ref; - T2, OR: 0.849, 95% CI: 0.696, 1.035; - T3, OR: 0.738, 95% CI: 0.595, 0.916; DQI (total) & OW; - T1, OR: 1, ref; - T2, OR: 0.94, 95% CI: 0.77, 1.15; - T3, OR: 0.77, 95% CI: 0.62, 0.96; - Per SD, OR: 0.93, 95% CI: 0.84, 1.02 | - Did not account for: Race/Ethnicity; - DQI total score included diversity, adequacy, and equilibrium components for OW; DQI-DQ scale only and BMI/Ob extracted from supplemental table 8; Funding: Miljøforsk-Programme on Environmental Research for a Green Transition of the Norwegian Research Council
Temple, 2023 ^70^; United States; n/a; Analytic N=158; Selection data: Enrolled those in the Western NY area, speak and read English; willing to consume study foods; Excluded those with medications impacting appetite/body weight, conditions impacting consumption of study foods | Age at Dietary Pattern: 12 to 14y, mean 13.3y; DGA, 2020–2025: Yes/No to consuming Vegetables; Fruit; Whole grains; Dairy; Protein; Limit: Added sugars; Saturated fat; Sodium; Method: Index/Score Analysis | Results at age(s) 15.25y, mean at F/U; Yes v. No DGA & Δ zBMI, β: 0.084 (0.068), T: 1.23; F: 1.51; p-trend=0.22 | - Did not account for: Physical activity, SEP (all higher income/educated); - Indirectly examined via yes/no to DGA alignment; Energy Intake & zBMI over 24 months was moderated by DGA alignment (β: −0.0008 (0.0003), T: −1.99; F: 3.99; p-trend=0.048); primary interest in reinforcing value and energ-density of food, not dietary patterns; Smaller sample size with relatively high attrition ~30%; Funding: NIH
Tognon, 2014 ^71^; Italy, Estonia, Cyprus, Belgium, Sweden, Hungary, Germany, Spain; IDEFICS (Identification and prevention of Dietary- and lifestyle-induced health EFfects In Children and infantS) study; Analytic N=9114; Selection data: Excluded those with missing data | Age at Dietary Pattern: 2 to 9 y; frequency-based MDS (fMDS) [Tognon, 2014]: Positive: Vegetables and legumes, fruit and nuts (fruit added or not with sugar, nuts, seeds, dried fruit), cereals (breakfast cereals, white and wholemeal bread, rolls and crispbread, pasta, noodles and rice), fish (fresh or frozen fish, and fried fish and fish fingers; Negative: Dairy (milk, yoghurt, cheese including spreadable cheese), and meat products (fried and non-fried meat, hamburgers, falafel, kebab, etc.); Method: Index/Score Analysis | Results at age(s) F/U: 2y, age ~ 4–11y; - Δ Q5, High BMIz, OR: 0.87, 95% CI: 0.78, 0.98; p≤0.05; - Δ Q5, High %FM, OR: 0.89, 95% CI: 0.78, 1; p=0.06; - Δ Q5, High WHR, OR: 0.88, 95% CI: 0.78, 0.99; p≤0.05; - Δ Q5, High WC, OR: 0.87, 95% CI: 0.77, 0.98; p≤0.05 | - Did not account for: Race/ethnicity NR; - Dietary pattern comparison groups not clearly described (“High” included wide range, scores > 3 from scale 0–9); Diet measured once at baseline; Did not account for missing data; Funding: European Union within the Sixth RTD Framework Program; Swedish Council on Working Life and Social Research (FAS) EpiLife Center and the Swedish Research Council
Vallejo, 2022 ^72^; Germany; DONALD (Dortmund Nutritional and Anthropometric Longitudinal Designed) Study; Analytic N=298 final sample; 284 sensitivity analysis; Selection data: Excluded those <15y; had <2 WDR; missing data; underreported EI; multiple birth pregnancies; low birth weight; preterm pregnancy; those with a long f/up time | Age at Dietary Pattern: 15 y and older; Dietary index (DI) score from the EAT-Lancet Reference Diet [Vallejo, 2022]: Positive: Whole grains & all grains, ≤ 464 g/d and whole grain fiber; Tubers or starchy vegetables, ≤ 100 g/d; Vegetables, ≥ 200 – ≤ 600 g/d; Fruits, ≥ 100 – ≤ 300 g/d; Dairy foods, ≤ 500 g/d; Beef and lamb, ≤ 14 g/d; Pork, ≤ 14 g/d; Chicken and other poultry, ≤ 58 g/d; Eggs, ≤ 25 g/d; Fish, ≤ 100 g/d; Dry beans, lentils & peas, ≤ 100 g/d; Soy foods, ≤ 50 g/d; All nuts, ≥ 25 g/d; Palm oil, ≤ 6.8 g/d; Unsaturated oils, ≥ 20 – ≤ 80 g/d; Lard or tallow, ≤ 5 g/d; Butter, 0 g/d; All sweetners, ≤ 31 g/d; Method: Index/Score Analysis | Results at age(s) 18y; BMI; - Continuous: β: 0.99, 95% CI: 0.97, 0.99; p = 0.004; - T1: β: 22.9, 95% CI: 22.0, 23.9; - T2: β: 22.5, 95% CI: 21.6, 23.5; - T3: β: 21.9, 95% CI: 20.9, 22.8; - p = 0.030; FFMI; - Continuous: β: 0.99, 95% CI: 0.99, 0.99; p = 0.034; - T1: β: 16.9, 95% CI: 16.3, 17.5; - T2: β: 16.8, 95% CI: 16.2, 17.4; - T3: β: 16.6, 95% CI: 16.1, 17.2; - p = 0.514; BF %; - Continuous: β: 0.98, 95% CI: 0.96, 0.99; p = 0.049; - T1: β: 25.1, 95% CI: 22.6, 27.9; - T2:; WC; - Continuous: β: 0.99, 95% CI: 0.98, 0.99; p = 0.022; - T1: β: 77.1, 95% CI: 74.8, 79.4; - T2: β: 76.3, 95% CI: 74.1, 78.6; - T3: β: 74.9, 95% CI: 72.7, 77.1; - p = 0.089; BW; - Continuous: β: 0.98, 95% CI: 0.97, 0.99; p = 0.002; - T1: β: 70.5, 95% CI: 67.3, 73.8; - T2: β: 69.4, 95% CI: 66.4, 72.7; - T3: β: 67.6, 95% CI: 64.6, 70.7; - p = 0.117 | - Did not account for: Anthropometry (adjusted for birthweight), Race/Ethnicity, Physical activity; - Sensitivity analyses by sex: DI score & continuous Weight (p = 0.036) and continuous BMI (p = 0.020) for males; tertiles & DBP (0.039) for females; After removal of long follow-up: continuous DI score & Weight, BMI, FFMI, WC, Body fat %; Tertiled DI score & BMI; Using standardized kcal/d for males & females: similar results (data NR); Funding: German Federal Ministry of Education and Research grant, Ministry of Science and Research of North Rhine Westphalia, Germany
Vedovato, 2021 ^73^; Portugal; Generation XXI; Analytic N=1175; Selection data: Excluded those without 2-d food diaries; missing CEBQ data; congenital anomalies or diseases that might influence dietary intake; twins; missing data | Age at Dietary Pattern: 4 y; 7 y; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Soft drinks; sweet or savoury packaged snacks; ice cream, chocolate, candies; massproduced packaged breads and buns; margarines and spreads; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; flavoured and/or artificial sweetened yoghurt; Method: Index/Score Analysis | Results at age(s) 10y; UPF at 4y & zBMI at 10 y; - β: 0.028, 95% CI: 0.006, 0.051; UPF at 7y & zBMI at 10y; - β: 0.014, 95% CI: −0.007, 0.036 | - Did not account for: Race/Ethnicity (100% Portugese-birth cohort); - Data NR for sensitivity analyses by UPF in % Total Energy (only per 100 kcal); Funding: Portuguese Ministry of Education and Science; Health Operational Programme; Community Support Framework III; Regional Department of Ministry of Health
Vilela, 2022 ^74^; Portugal; Generation XXI; Analytic N=3034; Selection data: Excluded those with missing diet/anthro data; twins; and those with congenital anomalies or diseases impacting food intake | Age at Dietary Pattern: 7y; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) e.g. Carbonated beverages, fruit-based beverages and other sugar-sweetened beverages; flavored and/or artificial sweetened yoghurt and milk based drinks; sweet or savory packaged snacks; ice-cream, chocolate, candies; mass-produced packaged breads and buns; margarines and spreads; ultra-processed cheeses; cookies, pastries and cake mixes; breakfast cereals and cereal/energy bars; milk, cocoa and fruit drinks; meat and chicken extracts and instant sauces; infant formulas, follow-on milks and other baby products; ready-to-heat/eat products and dishes (pies, pasta, pizza, desserts); processed meats and sausages; packaged soups and noodles; food supplements and artificial sweeteners.; Method: Index/Score Analysis: UP, Nova | Results at age(s) 10y; Growth/Body composition:; - Nova 4 & FMz, β:−0.006, 95% CI: −0.022, 0.011; - Nova 4 & FFMz, β:0.012, 95% CI: −0.005, 0.029; - Nova 3 & FMz, β:−0.002, 95% CI: −0.043, 0.040; - Nova 3 & FFMz, β:0.037, 95% CI: −0.005, 0.079; - Nova 2+1 & FMz, β:−0.023, 95% CI: −0.035; −0.011; - Nova 2+1 & FFMz, β: 0.002, 95% CI: −0.010, 0.014; - Nova 4 & BMIz, β:−0.009, 95% CI: −0.029, 0.011; - Nova 3 & BMIz, β:0.010, 95% CI: −0.040, 0.061; - Nova 2+1 & BMIz, β:−0.028, 95% CI: −0.043; −0.014; - Nova 4 & WCz, β:−0.003, 95% CI: −0.019, 0.014; - Nova 3 & WCz, β:0.005, 95% CI: −0.037, 0.046; - Nova 2+1 & WCz, β:−0.020, 95% CI: −0.032; −0.008; - Nova 4 & WCz, β:−0.003, 95% CI: −0.019, 0.014; - Nova 3 & WCz, β:0.005, 95% CI: −0.037, 0.046; - Nova 2+1 & WCz, β:−0.020, 95% CI: −0.032; −0.008 | - Did not account for: Age; Race/Ethnicity (Portuguese birth-cohort); - Diet assessed only once with 3d food diaries at 7y; Outcomes objectively measured; Funding: FEDER through the Operational Programme Factors of Competitiveness, COMPETE; Foundation for Science and Technology, FCT; Unidade de Investigaç~ao em Epidemiologia - Instituto de Saúde Pública da Universidade do Porto (EPIUnit); the Laboratorio para a Investigaç~ao Integrativa e Translacional, ITR.
Vinke, 2020 ^75^; Netherlands; GECKO Drenthe birth cohort; Analytic N=1001; Selection data: Enrolled participants at birth; Excluded those with birth weight < 2500 g; missing dietary data or BMI at age 3 or 10 y | Age at Dietary Pattern: 3 y; [underlined: Lifelines Diet score (LLDS)] [Vinke, 2018]: Positive: Vegetables; Fruits; Legumes and Nuts; Whole-grain products; Fish; Unsweetened dairy; Oils and soft margarines; Tea; Negative: Negative: Red and processed meats; Butter and hard margarines; Sugar-sweetened beverages; Method: Index/Score Analysis | Results at age(s) 10y; Ob/OW; - Q1, OR: 2.55, 95% CI: 1.13, 5.76; - Q2, OR: 1.82, 95% CI: 0.81, 4.09; - Q3, OR: 3.14, 95% CI: 1.39, 7.10; - Q4, OR: 1.72, 95% CI: 0.75, 3.92; - Q5, OR: 1.00, ref; - p-trend=0.044; Δ zBMI, β: −0.043, 95% CI: −0.079, −0.007; p-trend= 0.019 | - Did not account for: Race/Ethnicity, Physical activity; - Diet assessed with validated FFQ at baseline (age 3y) only; Those LFU hasd slightly higher BMI and mothers with lower education levels; Physical activity data were not available; Funding: Hutchison Whampoa Ltd., Hong Kong; University of Groningen, Well Baby Clinic Foundation Icare, Noordlease, Paediatric Association Of the Netherlands, and Youth Health Care Drenthe
Wolters, 2018 ^76^; Germany; KOPS- and IDEFICS- only German cohorts; Analytic N=372 KOPS; N=312 IDEFICS; Selection data: NR | Age at Dietary Pattern: 5 to 7y KOPS; 2 to 9.9y IDEFICS; [underlined: KOPS]; PCA 1 ‘Fast food’: High loadings for fish sticks, curry-sausage, lasagna, pancakes, potato fritters, pizza, meatballs; PCA 2 ‘Healthy’: Higher loadings for vegetables, fruits, whole grains, muesli, cheese-curd-yogurt; ΔPCA1: Increased meatballs, fish sticks, lasagna, pizza, pancakes, curry-sausage, potato fritters; ΔPCA2: Increased vegetables, fruits, meat, potatoes; ΔPCA3: Increased white bread, savory baked goods, decreased whole grain bread; RRR1, ‘Fast food’: Higher intake of lemonade, children’s yogurt, potato fritters, meat balls, meat; lower whole grain bread, cheese-curd-yogurt; ΔRRR1: Increased fast foods and starchy carbohydrate (whole grain brad, potatoes, pizza, fish sticks); decreased vegetables; [underlined: IDEFICS]; PCA 1 ‘Snack’: High loadings for sweet snacks, potatoes; ketchup etc.; savory snacks; sweetened drinks; chocolate, candy bars; candies, ice cream/milk/fruit-bars; PCA 2 ‘Mediterranean type’: Higher loadings for plain unsweeteend yogurt; milled cereal dish; nuts, seeds, dried fruits; pizza as main; cheese; fresh meat not fried; plain unsweetened milk; fresh fruits w/o added sugar; water; pasta noodles, rice; ΔPCA1 to PCA2: Increased nuts, seeds, dried fruits; pasta noodles, rice, fresh meat not fried; pizza as main; milled cereal dish; sweet yogurt, fermented milk; fried meat; ΔPCA2 twds ‘Traditional’: Increased cooked vegetables, potatoes, beans, legumes; sweetened drinks; butter, margarine on bread; fresh fruits w/o added sugars; ΔPCA3 to PCA1: Increased sweet snacks, candies, ice cream/milk/fruit-bars, savory snacks; chocolate, candy bars; RRR1, ‘nuts, meat, pizza’: nuts, seeds, dried fruits; fresh meat not fried; pizza as main; plain unsweeteend yogurt; jam, honey; savory pastries, fritters; milled cereal dish; low intakes of cooked vegetables potatoes, legumes, breakfast cereals, sweetened muesli; ΔRRR1: Higher reduced-fat products on breads; Lower fresh meat not fried, savory pastries, fried/scrambled eggs; sweetened drinks; nuts, seeds, dried fruits; milled cereal dish; Method: RRR; Factor/cluster PCA | Results at age(s) 9 to 11y KOPS; 4 to 11.9 y IDEFICS; KOPS DPs & BMI (T1, ref OR: 1); - RRR1 [‘Fast food]] & higher odds of excess BMI (p<0.0006); - ΔRRR1 [Increased Fast food/starchy carbs’] & higher odds of excess BMI (p=0.0004); PCA1; - T2, OR: 0.81, 95% CI: 0.44, 1.49; - T3, OR: 1, 95% CI: 0.55, 1.80; - Cont., OR: 1.01, 95% CI: 0.95, 1.07; p=0.8457; ΔPCA 1; - T2, OR: 0.95, 95% CI: 0.51, 1.75; - T3, OR: 1.49, 95% CI: 0.83, 2.68; - Cont., OR: 1.05, 95% CI: 0.99, 1.10; p=0.1133; PCA2; - T2, OR: 1.1, 95% CI: 0.62, 1.95; - T3, OR: 0.77, 95 % CI: 0.41, 1.43; - Cont., OR: 1, 95%CI: 0.91, 1.08; p=0.9079; ΔPCA 2; - T2, OR: 1.03, 95% CI: 0.57, 1.86; - T3, OR: 0.76, 95% CI: 0.42, 1.39; - Cont., OR: 0.98, 95% CI: 0.90, 1.08; p=0.7236; ΔPCA 3; - T2, OR: 0.89, 95% CI: 0.50, 1.61; - T3, OR: 0.9, 95% CI: 0.50, 1.63; - Cont., OR: 0.99, 95% CI: 0.88, 1.10; p=0.8046; IDEFICS DPs & BMI (T1, ref OR: 1); - RRR1 [‘Nuts, meat, pizza’] & odds of excess BMI (p=0.0036); - ΔRRR1 [‘Decreased protein/snack carbohydrates’] & higher odds of excess BMI (p=0.0029); PCA1; - T2, OR: 0.67, 95% CI: 0.35, 1.26; - T3, OR: 0.47, 95% CI: 0.23, 0.91; - Cont., OR: 0.94, 95% CI: 0.87, 1.01; p=0.081; ΔPCA1; - T2, OR: 1.12, 95% CI: 0.60, 2.11; - T3, OR: 0.65, 95% CI: 0.33, 1.30; - Cont., OR: 0.93, 95% CI: 0.87, 0.99; p=0.0436; PCA 2; - T2, OR: 0.65, 95% CI: 0.33, 1.27; - T3, OR: 0.92, 95% CI: 0.47, 1.79; - Cont., OR: 1.04, 95% CI: 0.99, 1.11; p=0.1403; ΔPCA 2; - T2, OR: 1.02, 95% CI: 0.52, 1.98; - T3, OR: 1.06, 95% CI: 0.54, 2.07; - Cont., OR: 1.02, 95% CI: 0.92, 1.14; p=0.6587; APCA 3; - T2, OR: 1.6, 95% CI: 0.83, 3.15; - T3, OR: 1.46, 95% CI: 0.75, 2.87; - Cont., OR: 1.02, 95% CI: 0.94, 1.11; p=0.6363; KOPS DPs & FMI (T1, ref OR: 1); - KOPS-RRR1 [‘Fast food]] & higher odds of excess FMI (p=0.2465); - KOPS-ΔRRR1 [Increased Fast food/starchy carbs’] & higher odds of excess FMI (p=0.0012); PCA1 & FMI; - T2, OR: 0.67, 95% CI: 0.37, 1.24; - T3, OR: 0.73, 95% CI: 0.41, 1.33; - Cont., OR: 0.99, 95% CI: 0.94, 1.06; p=0.8556; ΔPCA 1; - T2, OR: 1.19, 95% CI: 0.64, 2.21; - T3, OR: 1.86, 95% CI: 1.03, 3.38; - Cont., OR: 1.06, 95% CI: 1.00, 1.12; p=0.0411; PCA2; - T2, OR: 1.42, 95 %CI: 0.80, 2.53; - T3, OR: 0.89, 95% CI: 0.47, 1.67; - Cont., OR: 1, 95% CI: 0.92, 1.09; p=0.9971; ΔPCA 2; - T2, OR: 0.86, 95% CI: 0.47, 1.57; - T3, OR: 0.92, 95% CI: 0.51, 1.65; - Cont., OR: 1, 95% CI: 0.91, 1.09; p=0.9852; ΔPCA 3; - T2, OR: 0.75, 95% CI: 0.41, 1.35; - T3, OR: 0.96, 95% CI: 0.53, 1.72; - Cont., OR: 0.97, 95% CI: 0.87, 1.09; p=0.6091; IDEFICS DPs & FMI (T1, ref OR: 1); - RRR1 [‘Nuts, meat, pizza’] & odds of excess FMI (p=0.0090); - RRR1 [‘Decreased protein/snack carbohydrates’] & higher odds of excess FMI (p=0.0030); PCA1; - T2, OR: 1.06, 95% CI: 0.55, 2.03; - T3, OR: 0.78, 95% CI: 0.39, 1.52; - Cont., OR: 0.98, 95% CI: 0.91, 1.05; p=0.6013; ΔPCA1; - T2, OR: 1.05, 95% CI: 0.55, 1.99; - T3, OR: 0.79, 95% CI: 0.40, 1.56; - Cont., OR: 0.94, 95% CI: 0.87, 0.99; p=0.049; PCA2; - T2, OR: 1, 95% CI: 0.52, 1.92; - T3, OR: 0.91, 95% CI: 0.46, 1.81; - Cont., OR: 1.05, 95% CI: 0.99, 1.12; p=0.1073; ΔPCA 2; - T2, OR: 1.02, 95% CI: 0.53, 1.96; - T3, OR: 0.83, 95% CI: 0.42, 1.63; - Cont., OR: 0.99), 95% CI: 0.89, 1.10; p=0.878; ΔPCA3; - T2, OR: 1.27, 95% CI: 0.65, 2.50; - T3, OR: 1.49, 95% CI: 0.78, 2.90; - Cont., OR: 0.99, 95% CI: 0.91, 1.08; p=0.8546; KOPS DPs & WHR; - RRR1 [‘Fast food]] & higher odds of excess WHR (p=0.0047); - ΔRRR1 [Increased Fast food/starchy carbs’] & higher odds of excess WHR (p=0.0015); PCA1; - T2, OR: 0.54, 95% CI: 0.29, 1.01; - T3, OR: 0.88, 95% CI: 0.49, 1.57; - Cont., OR: 1, 95% CI: 0.95, 1.06; p=0.9329; ΔPCA 1; - T2, OR: 0.79, 95% CI: 0.43, 1.46; - T3, OR: 1.35, 95% CI: 0.76, 2.40; - Cont., OR: 1.02, 95% CI: 0.97, 1.08; p=0.3665; PCA 2; - T2, OR: 0.97, 95% CI: 0.55, 1.72; - T3, OR: 0.72, 95% CI: 0.39, 1.34; - Cont., OR: 1, 95% CI: 0.92, 1.09; p=0.9676; ΔPCA 2; - T2, OR: 0.61, 95% CI: 0.33, 1.13; - T3, OR: 0.8, 95% CI: 0.45, 1.43; - Cont., OR: 0.96, 95% CI: 0.88, 1.05; p=0.3628; ΔPCA 3; - T2, OR: 0.92, 95% CI: 0.52, 1.64; - T3, OR: 0.71, 95% CI: 0.39, 1.30; - Cont., OR: 0.92, 95% CI: 0.82, 1.03; p=0.1262; IDEFICS DPs & WHR; - RRR1 [‘Nuts, meat, pizza’] & higher odds of excess WHR (p=0.0019); - ΔRRR1 [‘Decreased protein/snack carbohydrates’] & higher odds of excess WHR (p<0.0001); PCA1; - T2, OR: 1.18, 95% CI: 0.62, 2.28; - T3, OR: 0.95, 95% CI: 0.48, 1.87; - Cont., OR: 0.98, 95% CI: 0.92, 1.05; p=0.6481; ΔPCA1; - T2, OR: 1.04, 95% CI: 0.55, 1.99; - T3, OR: 0.79, 95% CI: 0.40, 1.56; - Cont., OR: 0.93, 95% CI: 0.87, 0.99; p=0.049; PCA2; - T2, OR: 0.6, 95% CI: 0.31, 1.17; - T3, OR: 0.86, 95% CI: 0.44, 1.67; - Cont., OR: 1.04, 95% CI: 0.98, 1.11; p=0.1764; ΔPCA 2; - T2, OR: 0.63, 95% CI: 0.32, 1.24; - T3, OR: 0.77, 95% CI: 0.40, 1.50; - Cont., OR: 0.94, 95% CI: 0.85, 1.04; p=0.2324; ΔPCA3; - T2, OR: 1.17, 95% CI: 0.59, 2.33; - T3, OR: 1.64, 95% CI: 0.86, 3.19; - Cont., OR: 1.03, 95% CI: 0.95, 1.12; p=0.4342 | - Did not account for: Race/Ethnicity (adjusted for migration in IDEFICS); Funding: Federal Ministry of Education and Research; Open Access Fund of the Leibniz Association; Additional funding for KOPS and IDEFICS studies separate

a Abbreviations: BMI, body mass index; BF, body fat (total unless otherwise specified as trunk, gynoid, android, etc.); BF%, body fat percentage; DP, dietary pattern; DQ, diet quality; EDF, energy-dense food; FFM, fat-free mass; FFMI, fat-free mass index; FM, fat mass (total, unless otherwise specified as trunk, gynoid, android, etc.); FMI, fat mass index; F/U, follow-up; HEI, Healthy Eating Index; NR, not reported; NS, not statistically significant; OR, odds ratio; Q, quantile; T, tertile; TEI, total energy intake; Wt, body weight

Table 11 Risk of bias for randomized controlled trials examining dietary patterns consumed by children and adolescents and growth, body composition, and risk of obesity.^a^

Article | Randomization | Deviations from intended interventions (effect of assignment or per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Asodeh, 2020^24^ | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Lee, 2020^49^ | LOW | LOW | LOW | LOW | LOW | LOW
Papamichael, 2019^59^ | LOW | HIGH | LOW | LOW | LOW | HIGH

a Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (August 2019 version)” Sterne JAC, Savovic J, Page MJ, . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898. doi:10.1136/bmj.l4898.)31462531

Table 12 Risk of bias for observational studies examining dietary patterns consumed by children and adolescents and growth, body composition, and risk of obesity.^a^

Article | Confounding | Exposure Classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Agnihotri, 2021^2^ | High | Low | Low | Low | High | Low | Low | High
Aljahdali, 2022^19^ | Low | Some concerns | Low | Some concerns | High | Low | High | High
Ambrosini, 2016^20^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Arenaza, 2020^21^ | High | Low | Low | Low | High | Low | Low | High
Arruda Neta, 2021^22^ | Low | Some concerns | Low | Low | High | Low | Low | Some concerns
Asghari, 2016^23^ | High | Low | Low | Low | Low | Low | Some concerns | High
Bawaked, 2020^25^ | Some concerns | High | Some concerns | Low | Low | Low | Low | High
Biazzi, 2017^27^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns | High
Bekelman, 2021^26^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Buckland, 2022^28^ | Some concerns | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Bull, 2016^29^ | High | High | Low | Low | High | Low | High | Very high
Chan She Ping-Delfos, 2015^30^ | Some concerns | Low | Low | Low | Some concerns | Low | Some concerns | Some concerns
Chang, 2021^31^ | Low | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Choy, 2020^32^ | High | High | Low | Low | High | Low | Some concerns | High
Costa, 2019^35^ | High | Low | Some concerns | Low | Low | Low | Some concerns | High
Costa, 2021^33^ | Some concerns | High | Low | Low | Low | Low | Low | High
Costa, 2022^34^ | Some concerns | High | Low | Low | Low | Some concerns | Some concerns | High
Costa, 2023^36^ | High | Some concerns | Some concerns | Low | High | Low | Some concerns | High
Cunha, 2018^37^ | High | High | Some concerns | Low | Low | Low | Low | High
Diethelm, 2014^38^ | High | Low | Low | Low | Some concerns | Low | Low | Some concerns
Durao, 2017^39^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Durão, 2022^40^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Farhadjenad, 2018^41^ | High | Low | Some concerns | Low | High | Low | Some concerns | High
Fernandez-Alvira, 2017^42^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Gasser, 2019^43^ | Low | Some concerns | Low | Low | Some concerns | Low | Some concerns | Some concerns
González, 2023^44^ | Some concerns | Very high | Low | Low | Low | Low | High | Very high
Heerman, 2023^45^ | High | Some concerns | High | Low | Low | Low | Some concerns | High
Hu, 2016^46^ | Low | Low | Low | Low | High | High | Some concerns | High
Johnson, 2008^47^ | High | Low | Low | Low | Low | Low | Some concerns | High
Krijger, 2021^48^ | Low | Low | Some concerns | Low | High | Low | Some concerns | High
Lioret, 2014^50^ | High | Low | Low | Low | High | Low | Some concerns | High
Luque, 2021^51^ | Some concerns | Low | Low | Low | Some concerns | Low | High | High
Marinho, 2022^52^ | Very high | Some concerns | Low | Low | Low | Low | High | Very high
Marks, 2015^53^ | High | High | High | Low | Some concerns | Low | Low | High
Martin-Calvo, 2016^54^ | High | Low | Low | Low | Some concerns | High | Some concerns | High
McCourt, 2014^55^ | Some concerns | Low | Low | Low | Some concerns | Low | Low | Some concerns
Nguyen, 2020^10^ | Some concerns | Low | Low | Low | Low | Low | High | High
Notario-Barandiaran, 2020^56^ | High | Low | Low | Low | Some concerns | Low | Some concerns | High
Oellingrath, 2017^57^ | Some concerns | Low | Some concerns | Low | High | Some concerns | Some concerns | High
Okubo, 2015^11^ | High | Low | Low | Low | High | Low | Some concerns | High
Pala, 2013^58^ | Some concerns | Low | Low | Low | High | Low | Some concerns | High
Pinto, 2021^60^ | Some concerns | Some concerns | Some concerns | Low | Low | Low | Some concerns | Some concerns
Rashid, 2020^61^ | High | Low | Low | Low | Some concerns | Low | Low | High
Saldanha-Gomes, 2017^62^ | Some concerns | Some concerns | Low | Low | Low | Low | Low | Some concerns
Saldanha-Gomes, 2022^63^ | Some concerns | High | Low | Low | Some concerns | Low | Low | High
Santos, 2019^15^ | High | Some concerns | Low | Low | Some concerns | Low | Some concerns | High
Setayeshgar, 2017^64^ | Some concerns | Low | Some concerns | Low | Low | Low | Low | Some concerns
Shinsugi, 2020^65^ | Some concerns | Some concerns | Low | Low | Some concerns | High | Low | High
Siddiqui, 2021^66^ | Low | Low | Low | Low | Some concerns | Low | Some concerns | Some concerns
Sirkka, 2021^67^ | High | Some concerns | Some concerns | Low | High | Low | Low | High
Smith, 2014^68^ | Low | Low | Some concerns | Low | Very high | Low | Some concerns | Very high
Sorensen, 2021^69^ | Some concerns | Some concerns | Low | Low | Low | Some concerns | Some concerns | High
Temple, 2023^70^ | High | Some concerns | Low | Low | Low | Low | Some concerns | High
Tognon, 2014^71^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Vallejo, 2022^72^ | High | Some concerns | Low | Low | Low | Low | Some concerns | High
Vedovato, 2021^73^ | Low | Some concerns | Low | Low | Some concerns | Low | Some concerns | Some concerns
Vilela, 2022^74^ | Low | Low | Some concerns | Low | Low | Low | Some concerns | Some concerns
Vinke, 2020^75^ | Some concerns | Low | Low | Low | Some concerns | Low | Low | Some concerns
Wolters, 2018^76^ | Some concerns | Low | Low | Low | High | Low | Low | High

a Possible ratings of low, some concerns, high, very high, no information, or not applicable were determined using the “Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)” tool (ROBINS-E Development Group ( Higgins J, Morgan R, Rooney A, . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

## Adults and older adults

The 2025 Dietary Guidelines Advisory Committee updates the existing systematic review^*^ by synthesizing an additional 106 articles that were published between January 2014 and May 2023 and met inclusion criteria by assessing how this new evidence relates to the conclusion statement from the existing systematic review. The 106 new articles examined the relationship between dietary patterns consumed by adults and older adults and body composition, and risk of obesity.^77–182^ Twenty-six articles came from interventions (20 RCTs) and 80 articles were from observational studies (79 prospective cohort studies, and 1 retrospective cohort study).(Table 16).

* Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

### Description of the evidence

#### Population

Sample size of study groups ranged from N=37 up to N=192,567. Most participants were followed for at least 6 months, but the follow-up duration across the body of evidence ranged between 3 months/12 weeks up to 4.8 years in intervention studies and from 6 months up to 30 years in observational studies.

Many studies exclusively enrolled those at high-risk for diet-related chronic disease, with 100% participants with overweight or obesity, 3 or more risk factors for metabolic syndrome, or other conditions such as hypertension or dyslipidemia. Participants’ mean BMI at baseline was 25 kg/m^2^ or greater, indicating overweight or obesity, in 68 articles.

Information on the race and/or ethnicity of participants was reported in 49 articles and included participants that were categorized as ”predominantly” White/Caucasian in 34 articles^44,84,87,89,92,94–97,99,102,105,108,109,132,140,142,143,156,162,163,165–167,169–171,173,174,177,178,182^ , 100% Puerto Rican^148^, 91% non-Hispanic Black ^175^, 87% non-White ^139^, 50–100% Chinese^138,140,144^, or ~40–50% ”Black” ^104,170^. Racial/ethnic minorities were generally under-represented across the evidence, such as those identifying as Asian and/or Pacific Islander, American Indian, Eskimo, Aleut, and/or Alaska Native. Several articles indicated participant heritage aligned with the country of conduct (e.g., Danish, Iranian, Italian, Japanese, Korean, Spanish). ^93,116,120–122,127,131,137,149,151,152,161,179,180^ The remaining articles did not report specific data on the race and/or ethnicity of participants.

Some information about the socioeconomic position (SEP) of participants was reported in 80 articles, but the type of data widely varied. Educational attainment was the most common type of SEP information reported and most participants received at least 13 years of education (i.e., some college).^44,77,79,81–83,85,88–91,93–95,97–100,104,105,109,112,117–120,123,128,131,135,136,140,142,144,148,154,157,170,171,174,175,178,181^ Some studies reported indicators of participant’s income and/or socioeconomic status.^44,83,86,92,96,97,100,105,109,113–115,122,136,139,140,142,143,148,154,161,165,171,175,181^

Studies were conducted in 22 different countries: Australia; Brazil; Canada; China; Croatia; Denmark; Finland; France; Greece; Iran; Italy; Japan; Korea; Mexico; Netherlands; Singapore; Spain; Sweden; Switzerland; United Kingdom; and the United States. Two articles studied participants across multiple European countries.^164,166^ Multiple articles with data from a single cohort were included but examined either different dietary patterns, outcomes, and/or sub-sets of participants: Australian Longitudinal Study on Women's Health (ALSWH); BIOBANK; China Health and Nutrition Survey (CHNS); China Nutrition and Health Survey; CoLaus | PsyColaus study; Coronary Artery Risk Development in Young Adults (CARDIA); ELSA-Brasil; European Prospective Investigation into Cancer (EPIC); Health Professionals Follow-Up Study (HPFS) and/or Nurse’s Healthy Study (NHS I, II); Korean Genome and Epidemiology Study (KoGES); MEDLey; Multi-ethnic Cohort (MEC); NutriNet-Sante; (PREDIMED); PREDIMED Plus; SUN Cohort; Tehran Lipid and Glucose study; Women’s Health Initiative (WHI).

#### Intervention/exposure and comparator

Most studies used a validated food-frequency questionnaire or 24-hour recalls to assess dietary intake. Diet was assessed once only in 29 articles ^77,79,84,87,89,97,101,103,105,107,109,112,122,123,125,134,135,148,149,152,154,155,158,161,164,168,178^

Dietary pattern methods included:

- Investigator-assigned dietary intervention^81,85,93–95,98,104,106,108,113–115,120,124,139,144,145,153,156,157,159,162,169,174,175,177^
- A priori Index/Score derivation ^44,77–80,82,83,86–91,97,99–103,105,109–112,116–119,121–123,125,127–134,136,138,143,146–149,152–155,158,160,161,163,164,166–168,170,172,173,178–182^ , including 6 from RCTs ^93,104,108,156,175,177^ and several examining “UPF” via Nova food classification system^88,97,103,132,136,149,161^
- Factor/cluster or latent-class analysis^84,87,107,135,151^
- Reduced rank regression^92,126,137,141,142,171^

Labels or names of dietary patterns varied across studies, with examples including “Mediterranean” style indices, DASH diet scores, dietary guideline-related scores such as the Healthy Eating Index (HEI), plant-based diet indices, “Prudent”, and “Western” dietary patterns. A visualization of all dietary pattern components in each dietary pattern examined in relation to outcomes of interest is available in Appendix 6: Dietary pattern visualization.

#### Outcomes

Most studies used standard protocols to measure weight, height, and/or waist circumference of participants, with exception of 21 articles that used self-reported weight, height and/or waist circumference for reported outcomes.^44,78,79,83,88,89,100,110,111,117–119,128,129,166,167,172,173,179,181,182^ Across the body of evidence, the following outcomes were reported:

- Weight (gain, loss) ^44,79–81,85,93–95,98,102,104,106,108,110,113–115,117,119,120,124,128,129,134,138,139,144,145,153,156,157,159,162,164,167,169,172,174,175,177–179,182^
- Fat-mass or body fat (e.g., kg or %)^81,85,95,99,101,104,120,121,125,132,141,142,144,146,147,158,161,171,175^
- Waist Circumference, Waist-hip ratio, Abdominal Obesity^77,81,83,85,87,89,92,93,95,98,99,102,106,108,112–114,116,120,123,124,127,128,131,136,137,141,142,144,145,148,152,155,157,159,161,162,164,168–170,175,177^
- BMI^81,85–89,92,93,95,98,100–102,104–106,113–116,119,120,122,124,126,128,130,135,141,143,145–148,153,154,157,160,161,166,171,175,179,180^
- Risk of Overweight and/or Obesity^77,82,88,89,92,97,100,110,114,117–119,133,136,141,142,149,161,181^

### Synthesis of the evidence

In 79 of 106 articles (12 RCTs; 67 observational), dietary patterns consumed by adults and older adults were associated with significantly lower risk of overweight/obesity and less gain in or lower body weight, BMI, waist circumference, and adiposity. Most of these associations reached statistical significance. These dietary patterns shared emphasis on vegetables, fruits, nuts, legumes, whole grains, fish/seafood and were generally lower in red and processed meats, refined grains, and sugar-sweetened foods and beverages. Many of the dietary patterns included dairy and/or dairy products as well as alcoholic beverage components, but considerably varied in scoring procedures (e.g., positive or negative) and specificity of select components.

Dietary patterns consumed by adults and older adults were associated with higher risk of overweight/obesity and greater gain in BMI and waist circumference in 24 of 106 articles (1 RCT; 23 observational). The magnitude and statistical significance of these associations varied. In addition, specific components of these dietary patterns varied, but most reflected higher intakes of processed meats, refined grains, sugar-sweetened foods and beverages, and (food sources of) saturated fats.

“Mediterranean”-style scores showed statistically significant associations with lower (or less gain) in weight, BMI, WC, WHR or lower risk of abdominal obesity, lower fat mass, trunk fat, visceral fat, or greater fat-free mass, and/or lower risk of overweight or obesity in 19 articles.^77,82,89,91,99,105,111,112,121,122,125,129,133,134,143,147,152,160,164,166,170,173,179^All or most of these “Mediterranean” indices scored the following components positively: vegetables (not potatoes), fruit, legumes, nuts, fish, and unsaturated vegetable oils/fats; and; positive or positive in moderation: alcoholic beverages; and negatively: red and processed meat, sugar-sweetened beverages. Most of these scores also reflected higher intakes of whole grains and/or cereal grains that were not refined explicitly. A few studies reported no statistically significant associations between a “Mediterranean” style diet index and outcomes ^112,134,152^ or unclear/mixed results ^91^.

“DGA-related” such as the Healthy Eating Index (HEI)-2005, HEI-2010, HEI-2015, or alternative HEI-2010, showed statistically significant associations with lower or less gain in: weight, WC, WHR or risk of abdominal obesity, BMI, adiposity and/or greater fat-free mass.^80,83,87,99,111,121,122,129,138,146–148,179,182^. All or most of these DGA-related indices scored the following components positively: vegetables (not potatoes), fruit, legumes and nuts, and unsaturated relative to saturated fats; positive in moderation: alcoholic beverages; and negatively: red and processed meats, foods with/intake of trans, solid and/or saturated fats; sugar-sweetened foods and/or beverages including fruit juice, and sodium. Several studies included scores (i.e., HEI-2010) with total protein foods and seafood/plant proteins as positive components and refined grains as negative components. One study found higher AHEI-2010 scores were significantly associated with favorable outcomes, but reported no significant associations when examining HEI-2005 scores in the same participants.^148^ One article reported findings in mixed directions: high adherence (Q1 or Q2 vs. Q5) to the HEI-2010 was significantly associated with [underlined: higher risk] of self-reported weight gain ≥ 10% after 1 year follow-up in postmenopausal women, who were predominantly non-Hispanic White. Notably, most women in this sample gained weight and the analyses did not account for alcoholic beverage intake. Results aligning with much of the other evidence (i.e. lower risk of weigh gain) were found in unadjusted analyses, when examining other dietary patterns, and in sensitivity analyses of this sample e.g., high adherence (Q1 or Q2 vs. Q5) to a “low-fat” diet was significantly associated with [underlined: lower risk] of self-reported weight gain≥ 5%.^109^

‘DASH’ style scores showed statistically significant associations with lower or less gain in weight and/or adiposity (e.g., BMI, WC) in 8 articles.^99,116,138,147,179^ All of these “DASH”-style indices scored the following components positively: vegetables (not potatoes), fruit and fruit juice, legumes and nuts, whole grains and low-fat dairy and negatively: red and processed meat, sugar-sweetened beverages, and sodium. Two articles reported no statistically significant associations between DASH-style scores and WC ^148,155^, BMI, or WHR ^148^, but did report favorable associations between other dietary scores and outcomes.

Other scores were associated with statistically, significantly lower or less gain in weight, BMI and/or risk of overweight/obesity in 20 articles.^44,83,89,91,101,102,105,109,110,117,118,123,127,130,131,143,148,155,163,167,168,172,178,180^ Examples of these scores include the a priori Diet Quality Score, the Global Diet Quality score, the Plant-Based Diet Index (PDI), the healthful PDI, and/or the unhealthful PDI, and the Provegetarian Food Pattern. Most of these scores shared the following components and scored them positively: vegetables, fruit, legumes, whole grains and negatively: red and processed meat, and saturated fats/butter. Most of these scores did not include a component for alcoholic beverage intake. Some variations between scores included scoring fish and/or seafood and lean meat differently (that is, about half scored these positively while the other half scored negatively due to emphasis on a plant-based diet). Additional one-off components included: “ultra-processed foods” (UPF), “purchased deep-fried foods”, and/or “miscellaneous animal foods” each scored negatively; and chocolate, diet soft drinks, and pickled foods each scored positive within moderation. Six of these articles also reported direct associations between [underlined: higher] [underlined: unhealthful] PDI scores and [underlined: higher] weight gain.

Country-specific scores were associated with outcomes such as lower or less gain in weight, adiposity, and/or lower risk of overweight/obesity that reached statistical significance in 6 of 11 articles ^78,79,100,119,128,154^including. Five of the articles reported data in Australian participants from three different cohort studies. Most of these scores shared the following components scored positively: vegetables, fruit, legumes, whole grains (or non-refined cereals), fish and/or seafood; and negatively: red and processed meat. Scores had variation between components and scoring, such as alcoholic beverage intake scored positively in moderation, negatively or negatively if greater than moderate (≥10 drinks/week), or positively scored total protein foods, including nuts and lean meats.

Dietary patterns with varying amounts of UPF were all statistically, significantly associated with higher adiposity and body weight outcomes in 10 (of 10) articles using the Nova food classification system of UPF. All of these patterns reflected higher intakes of processed meat; commercial-baked goods, refined grains (i.e., cookies; pastries; breakfast cereals), or sugar-sweetened foods (e.g., chocolate, sugar/confectionary) and beverages (e.g., iced tea, fruit drinks in bottles); saturated fats (i.e., margarine).

Dietary patterns based on reduced-rank regression were statistically, significantly associated with higher adiposity and body weight outcomes in 6 of the 6 articles using that approach.^92,126,137,141,142,171^ Dietary pattern components varied but shared the following commonalities: higher intakes of refined grains (e.g., ‘low-fiber’ or ‘white’ bread) and/or sugar-sweetened foods and beverages (e.g, chocolate, confectionary, soft drinks, juice, cake, cookies), and food sources of saturated fats (i.e., butter, full-fat spreads). Two articles reported results in both directions based on the different dietary patterns examined, aligning with the overall body of evidence.^137,142^

Dietary patterns based on factor or cluster analysis in 6 articles followed similar themes identified above, but generally reported no statistically significant associations.^84,87,107,135,151^Specific components between these dietary patterns varied widely. Several of these articles reported results in both directions based on the different dietary patterns examined.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee updated the conclusion statement from an existing systematic review to answer the question, “What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?” based on their review of new evidence from an additional 106 articles published between January 2014 and January 2024 that met inclusion criteria examining dietary patterns consumed by adults and older adults and body composition and risk of obesity.(Table 13)

Table 13 Conclusion statement and grade for dietary patterns consumed by adults and older adults and growth, body composition, and risk of obesity

Conclusion Statement | Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish/seafood; and lower intakes of meats (including red and processed meats), refined grains and sugar-sweetened foods and beverages are associated with lower adiposity (body fat, body weight, BMI, and/or waist circumference) and risk of obesity. These dietary patterns also included higher intakes of unsaturated fats and lower intakes of saturated fats and sodium. This conclusion statement is based on evidence graded as moderate.
Grade | Moderate
Body of Evidence | 106 articles (26 RCT, 79 prospective and 1 retrospective cohort) assessed as they relate to the evidence in the existing review (38 articles)
Consistency | Minimal variation in direction and significance of findings
Precision | - Most of the interventions demonstrated adequate power/sample sizes.; - Many of the observational studies had large sample sizes and reported results with relatively narrow width of confidence intervals.
Risk of bias | - Some concerns with risk of bias due to important confounding domains not accounted for, namely race and/or ethnicity.; - Some concerns with risk of bias due to selection of reported results.
Directness | - Few concerns with directness: the populations, intervention/exposure, comparators, and outcomes were directly related to the systematic review question in many studies.
Generalizability | - Relative to the U.S. population, the dietary patterns and outcomes examined in many of the included studies are applicable. However, findings may be less generalizable to younger adults, those with lower education, and/or healthier individuals.

#### Assessment of evidence

The body of evidence includes 106 articles published since 2014, assessed as they relate to the evidence included in the existing review^*^ and examined the relationship between dietary patterns consumed by adults and older adults and body composition and/or risk of obesity. This body of evidence includes both large and small studies, including small studies with null findings, which makes publication bias less likely. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

* Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf

##### Consistency

The direction of findings was consistent with many studies supporting significant associations between consumption of dietary patterns higher in vegetables, fruits, and whole grains; fish/seafood; nuts; legumes; lower in red and processed meats, refined grains and sugar-sweetened foods and beverages and favorable outcomes such as lower risk of obesity, overweight, and/or abdominal obesity, and/or less gain in weight and/or adiposity (BMI). A smaller sub-set of evidence supported associations between dietary patterns [that varied more between components but generally were higher in processed meat; refined grains and/or sugar-sweetened foods, sugar-sweetened beverages; and food sources of saturated fats] and unfavorable outcomes that included primarily higher risk of and/or greater gain in weight and adiposity. Effect sizes ranged in magnitude across the body of evidence, with many articles reporting results with appreciable effects.

##### Precision

Most of the interventions demonstrated adequate power/sample sizes. Many of the observational studies had large sample sizes and reported results with relatively narrow width of confidence intervals.

##### Risk of bias

Studies had numerous risks of bias across domains, which have the potential to influence the results reported (see Table 15, Table 17). Most articles controlled for most key confounders with exception of race and/or ethnicity of participants. Many of the articles (49 of 106) reported using repeated measures to assess diet from baseline as well as during follow-up, but some (31 of 106) used only a single diet assessment and therefore may be at higher risk of exposure misclassification. Notably, studies that reported results from both diet at baseline as well as over time tended to report similar results between those analyses. Some of the articles (23 of 106) relied upon self-report for outcome measures and are therefore at higher risk of bias due to outcome measurement concerns. Some of the articles (16 of 106) are at higher risk of bias due to missing data. Because many of the included articles came from observational studies without pre-specified analytic plans and/or conducted multiple exposure and outcome analyses, the body of evidence tended to be at higher risk of bias for selection of reported results.

##### Directness

Several, but not all, of the interventions were designed to directly examine the relationship between dietary patterns and body composition and risk of obesity in the population of interest. In most of the observational studies, the populations, intervention, comparators, and outcomes of interest were directly related to the systematic review question.

##### Generalizability

The body of evidence included studies from a total of 22 countries with similar HDI classification as the U.S. Some studies (25 of 106) were conducted in the United States. Among the studies conducted in other countries, most examined dietary patterns that are applicable to those consumed by Americans. Younger adults and those with lower education were under-represented in this body of evidence, but it is possible that findings are generalizable to them. The majority of participants in this body of evidence had overweight, obesity, or several risk factors for cardiometabolic disease, and therefore, are generalizable to the U.S. population.

Table 14 Evidence in adults and older adults from randomized controlled trials examining the relationship between dietary patterns consumed and body composition and risk of obesity^a^

Study Characteristics | Intervention/exposure and comparator | Results | Methodological considerations
Alvarez-Perez, 2016 ^81^; Spain; PREDIMED-Canarias; Analytic N=351; Participant characteristics:; Health: 92–97% Ob or OW; mean BMI ∼ 31; ∼83% HTN; ∼76–86% Dyslipidemia; ∼54–59% DM; ∼80% on anti-HTN-agents; Race and/or Ethnicity: NR; “Canarian”; SEP: Education: 85–91% primary; 7–11% secondary; ∼1% uni; Retired: ∼ 58–67%; Housewives: ∼19–22%; Workers 11–15% | Age at Dietary Pattern: 55 to 80 y at baseline; [underlined: Med+EVOO]: Assigned to abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO; [underlined: Med+Nuts]: Assigned to same diet as Med+EVOO in lieu of EVOO; + 15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts; [underlined: Control:] Advice to reduce dietary fat; Method(s): RCT | Follow-up duration: 1y; Med+EVOO; Med+Nuts; Control; - BF% : −0.1, 95% CI: −2.4, 2.2 v. 1.3, 95% CI: −1.4, 3.8; 3.3, 95% CI: 1.0, 5.7; p=0.136; - FM: 0.5, 95% CI: −2.4, 3.4; −0.2, 95% CI: −2.8, 2.4; 2.6, 95% CI: −0.4, 5.5; p=0.390; - FFM, −1.0, 95% CI: −2.4, 0.3 v. −0.8, 95% CI: −2.4, 0.8 v. −2.8, 95% CI: −4.0, −1.6; p=0.110; - Trunk FM%: 0.2, 95% CI: −2.8, 3.3; 3.9, 95% CI: −0.7, 8.5; 6.9, 95% CI: 0.8, 13.1; p=0.124; - Trunk FM, kg,: −0.6, 95% CI: −4.1, 2.9; 2.3, 95% CI: −3.8, 8.4; 9.0, 95% CI: −0.2, 18.1; p=0.100; - BMI: −1.1, 95% CI: −2.0, −0.2; −0.8, 95% CI: −2.3, 0.8; −1.1, 95% CI: −2.2, 0.2; p=0.877; - WC: −0.9, 95% CI: −2.0, 0.2; −2.2, 95% CI: −3.3, −1.0; −2.9, 95% CI: −4.1, −1.6; p=0.061; - Wt, kg: −1.1, 95% CI: −2.0, −0.2; −0.7, 95% CI: −1.7, 0.3; −1.2, 95% CI: −2.2, −0.3; p=0.657; Summary: NS/Null: Med+EVOO v. Med+Nuts v. Control & BMI, WC, Wt, % BF, FM, FFM, trunk Fat/FM at 1y | - Concerns with randomization related to the 2018 retraction and republication of primary data; - Indirect comparators in 2 arms of nuts v. EVOO relative to both Med diet arms v. Control; Funding: Instituto de Salud Carlos III (ISCIII) *; * Additional funding for Alvarez-Perez, 2016: Fondo de Investigaciones Sanitarias, Ministerio de Sanidad y Consumo RTICCentro de Investigac on Biomedica en Red de Fisiopatologıa de la Obesidad y Nutricion (CIBERobn); Agencia Canaria de Investigacion, Innovacion y Sociedad de la Informacion,Gobierno de Canarias
Arjmand, 2022 ^85^; Iran; Shiraz University of Medical Sciences; Analytic N=37; Participant characteristics:; Health: 100% OW/Ob, mean 41% BF, BMI 32; Race and/or Ethnicity: NR; SEP: Education, mean y: 16.4 v. 16.40 | Age at Dietary Pattern: 40–60 y at baseline; [underlined: MIND diet, calorie restricted]: Increased intake of green leafy vegetables, other vegetables, berries, fruits, beans [lentils, soybeans], whole grains, olive oil as the primary source of fat, fish and poultry (not fried); Decreased consumption of red meat and products, butter, fast fried foods, pastries and sweets (nuts remained similar); [underlined: Control, calorie-restricted]: Increased intake of green leafy vegetables, beans, olive oil as the primary source of fat, fish and poultry (not fried); Decreased consumption of nuts, whole grains, butter, fish not fried, fast fried foods, pastries and sweets; Method(s): RCT | Follow-up duration: 3mo; MIND v. Control; - Δ BF kg: 95% CI: −4.65, −0.77; p-trend<0.05; - Δ BF %: −5.16±0.82 v. −2.56±0.72; 4.96, 95% CI: −4.82, −0.36; η: 0.124; p-trend=0.03; - Δ FFM, kg: 2.54±0.52 v. 1.95±0.64; 0.49, 95% CI: −1.10, 2.28; η: 0.014; p-trend=0.48; - Δ BMI: −1.55±0.11 v. −0.92±0.07; 16.86; 95% CI: −0.91, −0.34; η: 0.325; p-trend<0.001; - Δ WC, cm, −3.54±0.56 v. −1.46±0.49; 6.74; 95% CI: −3.69, 0.43; η: 0.162; p-trend=0.01; - Δ Hip-C, cm, −2.27±0.23, v. −0.30±0.12; 37.66; 95% CI: −2.51, −1.26; η: 0.518; p-trend<0.001; - Δ Wt kg, −3.98±−0.29 vs. −2.34±0.17; 18.21; 95% CI: −2.41, −0.85; η: 0.342; p-trend<0.001; Summary: Significantly greater decrease in BF (kg or %), BMI, Wt, WC, Hip-C in the MIND vs. Control diet arms; NS/Null: ΔFFM (kg | - Small sample size; - Baseline serum leptin greater in MIND group (57.90±6.00 ng/mL) compared to control group (39.13±5.93 ng/mL), p=0.04;; - Participants refrained from PA and alcohol immediately prior to trial; Funding: Shiraz University of Medical Science, Shiraz, Iran
Bruno, 2020 ^93^; Italy; Fondazione IRCCS Istituto Nazionale dei Tumori di Milano; Analytic N=416; Participant characteristics:; Health:; - 100% women who were carriers of or had mutations in BRCA1/2; - Weight (kg): IG: 62.1±110.7; CG: 65.6±14.6; - BMI (kg/m2): IG: 23.9 ± 4.4, CG: 24.7± 5.1; - WC (cm): IG: 77.1 ± 11.7, CG: 79.0± 13.5; Race and/or Ethnicity: NR (Italian); SEP: Education: 1^st^ level ∼17%; 2^nd^ 44%; 3^rd^ level 39% | Age at Dietary Pattern: 18 to 70 y ♀ at baseline; [underlined: Intervention (IG) v. Control (CG)] had higher scores on Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011]: Positive: Vegetables; Dishes with Tomato Sauce (tomato, garlic, onion, leek, olive oil); Pulses; Fruit; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine. Negative: Commercial Pastries; Red Meat or Sausages; Animal fat; Sugar-Sweetened Beverages; [underlined: IG v CG:] assigned to follow a Mediterranean diet with restriction of animal protein to ∼11% TEI and refined foods, red and processed meats; received six cooking classes, conferences; encouraged to consume whole grains, nuts, and legume flours, and impove dietary habits; Method(s): RCT/Index | Follow-up duration: 6mo; IG v. CG; - Δ BMI, −0.6 v. −0.2; p<0.001; - Δ WC, −2.0 v. −0.7; p=0.01; - Δ HIP-C, −1.6 v. −0.5; p=0.01; - Δ Wt, −1.5 v. −0.5; p<0.001; Summary: Significantly greater decreases in BMI, Wt, WC, Hip-C among those with higher MEDAS (IG v. CG). | - At baseline, IG v. CG had significantly smaller Hip-C; - All female BRCA1/2 carriers or mutations; Funding: Italian Association of Cancer Research; Italian Ministry of Health
Calvo-Malvar, 2021 [underlined: A] ^94^; Spain; Galiat study; Analytic N=661; Participant characteristics:; Health: CVD, 16–18%; DM, 6%; Race and/or Ethnicity: 100% Caucasian; SEP:; - Employed ∼48–52%; Retired ∼14–20%; Other ∼32–34%; - Education: None, ∼10%; Elementary, 36–42%; Secondary 32–36%; Uni+ 16–18%; - Marital status: Partner 68–73%;Separated/Divorced/Widow 19–10%; Single 21–17% | Age at Dietary Pattern: 45y, mean; 3 to 85 y at baseline; [underlined: ‘Caloric’:] Positive: high-energy drinks, processed meats, precooked food, pizza, salty snacks, mayonnaise and ketchup, sweets. Negative: wine; [underlined: ‘Frieds’:] Positive: refined grains, fried meats, fried potatoes, fried fish, whole-fat dairy products, sunflower oil, sweets. Negative: low-fat dairy products, whole grains; [underlined: ‘Fruits, Veaetables, and Dairy Products’]: Positive: fruits, tea and herbal tea, honey, vegetables, nuts, olive oil, sweets, low-fat dairy products, whole grains; [underlined: ‘Alcohol’:] Positive: beer, liquors, wine, coffee, olive oil, processed meats; [underlined: ‘Fish and Boiled Meals’]: Positive: cooked/steamed/roasted meats, boiled potatoes, legumes, vegetables, boiled fish and seafood, fried or scrambled eggs, boiled or poached eggs, sunflower oil, fried fish; Method(s): RCT/Factor/Cluster | Follow-up duration: 6mo; Δ Wt (ITT); - Caloric, β: 0.146, −0.030, 0.332; p-trend=0.103; - Frieds, β: 0.240, 95% CI: 0.050, 0.429; p-trend=0.013; - Fruits, vegetables, and dairy products, β: −0.184, 95% CI: −0.379, 0.012; p-trend=0.063; - Alcohol, β: 0.026, 95% CI: −0.185, 0.237; p-trend=0.812; - Fish and boiled meats, β: −0.099, 95% CI: −0.262, 0.064; p-trend=0.234; Δ Wt (PP); - Caloric, β: 0.172, 95% CI: 0.002, 0.343; p-trend=0.047; - Frieds, β: 0.250, 95% CI: 0.065, 0.434; p-trend=0.008; - Fruits, vegetables, and dairy products, β: −0.186, 95% CI: −0.375, 0.002; p-trend=0.053; - Alcohol, β: 0.025, 95% CI: −0.177, 0.226; p-trend=0.881; - Fish and boiled meats, β: −0.074, 95% CI: −0.236, 0.089; p-trend=0.374; Summary: Significantly higher weight among those consuming a “Fried” (ITT or PP) or ‘Caloric’ (PP); NS/Null: Alcohol, Fruits, vegetables, and dairy products, Fish and boiled meats (ITT or PP, parents+children) & Wt | - Dietary data and results include children and adults, from ages 3 to 85 y; Funding: ERDF-Innterconecta for Galicia Program
Calvo-Malvar, 2021 [underlined: B] ^95^; Spain; Galiat study; Analytic N=661; Participant characteristics:; Health: CVD, 16–18%; DM, 6%; Race and/or Ethnicity: 100% Caucasian; SEP:; - Employed ∼48–52%; Retired ∼14–20%; Other ∼32–34%; - Education: None, ∼10%; Elementary, 36–42%; Secondary 32–36%; Uni+ 16–18%; - Marital status: Partnered 68–73%;Separated/Divorced/Widowed 19–10%; Single 21–17% | Age at Dietary Pattern: 39y, mean; 3 to 85 y at baseline; [underlined: Atlantic diet], Positive: breads, cereals, wholegrain cereals, rice, pasta, potatoes, olive oil, fruit, vegetables, dairy products, nuts (preferable chestnuts and walnuts), fish and seafood, eggs, lean meat, pulses. Negative: fatty meat, cured sausage, margarine, butter, sweets, pastries, cakes, ice cream; [underlined: Control]: usual dietary pattern; Method(s): RCT | Follow-up duration: 6mo; ITT, Atlantic vs. Control; - Δ%BF β: −0.85, 95% CI: −1.20, −0.50; p-trend<0.001; - ΔBMI, β: −0.44, 95% CI: −0.62, −0.25; p-trend<0.001; - ΔWHR, β: −0.012, 95% CI: −0.019, −0.005; p-trend=0.001; - ΔWt, kg (adults only, 18y+), β: −1.1, 95% CI: −1.6, −0.7; p-trend<0.001; PP; - Δ%BF, β: −0.88, 95% CI: −1.22, −0.53; p-trend<0.001; - ΔBMI, β: −0.45, 95% CI: −0.63, −0.27; p-trend<0.001; - ΔWHR, β: −0.013, 95% CI: −0.020, −0.006; p-trend<0.001; - ΔWt, kg (adults only, 18y+), β: −1.2, 95% CI: −1.7, −0.7; p-trend<0.001; Summary: Significantly greater decrease in Weight, BMI, WHR, %BF between Atlantic v. Control diet groups (in parents; ITT or PP); NS/Null children’s z-score | - Dietary data includes children and adults, from ages 3 to 85 y; - No adjustment for multiple testing was conducted;; - All participants were from one rural small community; Funding: ERDF-Innterconecta for Galicia Program
Casas, 2022 ^98^; Spain; PREDIMED; Analytic N=2278; Participant characteristics:; Health: At baseline: Q4 greater prevalence of HTN, DM compared to Q1. Q1 greater prevalence of current smoking, family Hx of premature CHD compared to Q4; Race and/or Ethnicity: NR; SEP: Higher educational attainment in Q1 compared to Q4 (data NR) | Age at Dietary Pattern: 59y (Q1); 74y (Q4), means at baseline; [underlined: MedDiets v. Control:] consumed higher fruit, legumes, fish and seafood; Q1 consumed higher vegetables and tea; [underlined: Med+EVOO]: Assigned to abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO; [underlined: Med+Nuts]: Assigned same diet as Med+EVOO, but in lieu of EVOO: + 15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts; [underlined: Control]: Advice to reduce dietary fat; Method(s): RCT | Follow-up duration: 3y; 3yΔ BMI, p-arm=0.036; p-age=0.04; p-inx=0.297; - ≤ 62y, All, −0.12, 95% CI: −0.22, −0.01; ○ MedDiet+EVOO: −0.09, 95% CI: −0.26, 0.08; ○ MedDiet+Nuts: +0.03, 95% CI: −0.15, 021; ○ Control arm, ≤ 62y: −0.28, 95% CI: −0.49, −0.08; - ≥ 71, All, −0.27, 95% CI: −0.38, −0.17; ○ MedDiet+EVOO −0.39, 95% CI: −0.55, −0.23; ○ MedDiet+Nuts: −0.14, 95% CI: −0.32, 0.04; ○ Control arm: −0.29, 95% CI: −0.48, −0.09; 3yΔ WC, cm, p-arm=0.601; p-age=0.519; p-inx=0.582; - ≤ 62y: All, +0.07, 95% CI: −0.33, 0.45; ○ MedDiet+EVOO: −0.02, 95% CI: −0.6, 0.6; ○ MedDiet+Nuts: +0.44, 95% CI: −0.2, 1.1; ○ Control arm: −0.23, 95% CI: −0.99, 0.53; - ≥ 71y: All −0.12, 95% CI: −0.49, 0.26; ○ MedDiet+EVOO: −0.01, 95% CI: −0.58, 0.56; ○ MedDiet+Nuts: −0.14, 95% CI: −0.81, 0.52; ○ Control arm: −0.19, 95% CI: −0.90, 0.52; 3yΔ Wt, kg, p-arm=0.024; p-age=0.002; p-inx=0.402; - ≤ 62y: All, −0.18, 95% CI: −0.46, 0.1; ○ MedDiet+EVOO: −0.15, 95% CI: −0.59, 0.29; ○ MedDiet+Nuts, +0.23, 95% CI: −0.24, 0.7; ○ Control arm, −0.61, 95% CI: −1.14, −0.08; - ≥ 71y All: −0.81, 95% CI: −1.08, −0.54; ○ MedDiet+EVOO: −1.08, 95 %CI: −1.5, −0.67; ○ MedDiet+Nuts: −0.47, 95% CI: −0.9, 0.002; ○ Control arm: −0.89, 95% CI: −1.39, −0.38; Summary: NS/Null: Med+EVOO or Med+Nuts & Δ BMI, Δ WC over 3y; Significantly greater Wt gain in Q1 and less Wt loss in Q4 of Med+Nuts v. Control arms | - Some concerns with baseline differences between groups; - Adjustment for multiple testing NR; Funding: Spanish Government, CIBERobn, Instituto de Salud Carlos III, Hojiblanca, Patrimonio Comunal Olivarero, California Walnut Commission, Borges SA, and Morella Nuts
Crosby, 2022 ^104^; United States; n/a; Analytic N=219; Participant characteristics:; Health: Lipid-Tx, 19% v. 17%; HTN-Tx, ∼27%; Thyroid-meds 13% v. 12%; Race and/or Ethnicity:; - White 47% v. 51%;; - Black 49% v. 41%;; - Asian, Pacific Islander 1% v. 6%; - American Indian, Eskimo, Aleut 2% v. 0%; - Did not dislose 4%; - Non-Hispanic 79% v. 85%; - Hispanic 7% v. 4%; - Not disclosed 15% v. 11%; SEP:; - Education: ≤HS, 6% v. 8%; Some college 15% v. 20%, College degree 17% v. 23%, Grad. degree 61% v. 50%; - Service 22% v. 12%; Technical ∼27%; Professional/Mgr 28% v. 33%; Retired 12% v. 20%; Other 10% v. 9% | Age at Dietary Pattern: 52.6y, mean (Vegan group), 56.5y (Control group); [underlined: Vegan vs. Control:] Higher AHEI-2010 scores; Significantly higher intakes of total starchy vegetables (non-fried); legumes; meat alternatives; total legumes and meta alternatives; whole grains; and significantly lower intake of fried vegetables; nuts and seeds; eggs; high-fat dairy; low-fat dairy; meat; fish and shellfish; poultry; total meat, fish and poultry; added sugars, oils, and animal fats; Similar intakes of fruit juice; avocado; dark green vegetables; and nut and seed butters; [underlined: Control:] Usual diet, no energy restriction; [underlined: Alternative HEI (AHEI-2010) [Chiuve 2012]]: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Method(s): RCT | Follow-up duration: 16 wks; Vegan vs. Control:; - FM (kg), t: −4.1, 95% CI: −4.7, −3.5; p-trend<0.001; - VAT, t: −238.3, 95% CI: −316.7, −159.9; p-trend<0.001; - BMI, t: −2.0, 95% CI: −2.4, −1.7; p-trend<0.001; - Wt, t: −5.9, 95% CI: −6.8, −5.0; p-trend<0.001; AHEI-2010, per 1-pt:; ○ FM, −0.14; p-trend=0.03; ○ Wt, r=−0.20; p-trend=0.003; Summary: Significant decreases in Wt, BMI, FM (kg) and VAT volume in Vegan v. Control groups; Higher AHEI-2010 scores were significantly associated with lower FM and Wt | Funding: Physicians Committee for Responsible Medicine
Davis, 2017 J Nutr ^106^; Australia; MedLey; Analytic N=166; All non-smokers, w/o chronic disease and major psychological illnesses; Participant characteristics:; Health: mean BMI ∼27; 33% v. 23% on lipid-lowering meds; Race and/or Ethnicity: NR; SEP: NR | Age at Dietary Pattern: ≥ 65 y, at baseline; [underlined: Mediterranean diet]: 15–45 mL EVOO/d, abundant vegetables, fruit, nuts, legumes, and whole grains, moderate fish, and avoid red meat (<1 serv/wk), small goods (salami, mettwurst, bacon, other processed meats); moderate red wine and dairy (cheese, yogurt) + written guide + recipe book + daily checklists + 30-min bimonthly session with RD [EVOO, nuts, legumes, and yogurt provided to participants]; [underlined: Habitual diet:] maintain usual intake, no new foods + written guide + $10 grocery voucher + 30-min bimonthly session with RD; Both groups reported as having “good compliance” with dietary protocols; Method(s): RCT | Follow-up duration: 3mo; 6mo; Mediterranean v. Habitual diet groups, mean differences in:; BMI, kg/m2; - at 3mo: −0.4, 95% CI: −0.31, 0.29, p=0.08;; - at 6mo: −0.3, 95% CI: −1.47, 0.98, p=0.94; WHR; - at 3mo: 0.00, 95% CI: −0.31, 0.29, p=0.75;; - at 6mo: −0.00 95% CI: −0.03, 0.03, p=0.18; Wt, kg; - at 3mo: −2.4, 95% CI: −6.6, 1.8, p=0.07;; - at 6mo: −1.9, 95% CI: −6.2, 2.4, p=0.10; Summary: NS/Null: Mediterranean compared to Habitual Diet groups did not differ in reductions of BMI or WHR after 3 or 6 months or Weight loss after 3 or 6 months | - Primary outcome was cognitive function - cardiometabolics were secondary; - Completers v. non-completers had similar baseline values except lower insulin in Habitual diet group; - Similar results were reported in multiple articles by study authors (excluded for data overlap); Funding: National Health and Medical Research Council of Australia
Estruch, 2019 ^108^; Spain; PREDIMED; Analytic N=3985; Participant characteristics:; Health:; - 100% high-risk for CVD; - ∼48% Diabetes; - mean Wt, ∼77kg;; - mean WC ∼100cm; WHR, 0.63;; - Smoking: never ∼61%, former ∼25%, current 14%; Race and/or Ethnicity: 97% white, European; SEP: NR | Age at Dietary Pattern: 67y, mean (55 to 80 y) at baseline; [underlined: Med+EVOO:] Consumed higher Fish/Seafood and Legumes and higher MEDAS scores than Control; Assigned to abundant olive oil, vegetables, fresh fruit and juices, legumes, fish or seafood, nuts and seeds, select white meat instead of red or processed meats, cook regularly with tomato, garlic and onion; wine preferred (if consuming alcohol); ad libitum nuts, eggs, fish, seafood, low-fat cheese, chocolate, whole-grain cereals + 15L EVOO; [underlined: Med+Nuts]: Consumed higher fish/seafood and legumes and higher MEDAS scores than Control; Assigned to same diet as Med+EVOO, but in lieu of EVOO: +15g/d walnuts, 7.5g/d almonds, and 7.5g/d hazelnuts; [underlined: Control:] Advised to reduce dietary fat; Method(s): RCT | Follow-up duration: 4.8 y, median; ΔWC, baseline at 1 y; - Med+EVOO v. Control, β: −0.313, 95% CI: −0.630, 0.004; p-trend=0.053; - Med+Nuts v. Control, β: −0.156, 95% CI: −0.493, 0.180; p-trend=0.362; ΔWC, baseline at 3 y; - Med+EVOO v. Control, β: −0.535, 95% CI: −1.071, 0.001; p-trend=0.051; - Med+Nuts v. Control, β: −0.209, 95% CI: −0.745, 0.327; p-trend=0.442; ΔWC, baseline at 5 y; - Med+EVOO v. Control, β: −0.466, 95% CI: −1.109, 0.176; p-trend=0.154; - Med+Nuts v. Control, β: −0.923, 95% CI: −1.604, −0.241; p-trend=0.008; β Average ΔWC; - Med+EVOO v. Control, β: −0.03, 95% CI: −0.13, 0.07; p-trend=0.54; - Med+Nuts v. Control, β: −0.11, 95% CI: −0.22, 0.01; p-trend=0.065; - In only age <70y; ○ Med+EVOO v. Control, β: −0.02, 95% CI: −0.14, 0.11; p-trend=0.77; ○ Med+Nuts v. Control, β: −0.11, 95% CI: −0.24, 0.03; p-trend=0.13; - In only age ≥70y; ○ Med+EVOO v. Control, β: −0·07, 95% CI: −0.22, 0.10; p-trend=0.49; ○ Med+Nuts v. Control, β: −0.11, 95% CI: −0.29, 0.06; p-trend=0.20; ΔWt after 1 y; - Med+EVOO v. Control, β: −0.006, 95% CI: −0.225, 0.213; p-trend=0.958; - Med+Nuts v. Control, β: 0.124, 95% CI: 0.113, 0.361; p-trend=0.306; - ΔWt after 3 y; - Med+EVOO v. Control, β: −0.326, 95% CI: −0.669, 0.016; p-trend=0.062; - Med+Nuts v. Control, β: −0.029, 95% CI: −0.383, 0.326; p-trend=0.874; ΔWt after 5 y; - Med+EVOO v. Control, β: −0.410, 95% CI: −0.830, 0.010; p-trend=0.056; - Med+Nuts v. Control, β: −0.016, 95% CI: −0.453, 0.421; p-trend=0.942; Average ΔWt per y; - Med+EVOO v. Control, β: −0.04, 95% CI: −0.11, 0.03; p-trend=0.24; - Med+Nuts v. Control, β: 0.05, 95% CI: −0.02, 0.12; p-trend=0.14; - In age <70y; ○ Med+EVOO v. Control, β: 0.01, 95% CI: −0.08, 0.10; p-trend=0.89; ○ Med+Nuts v. Control, β: 0.07, 95% CI: −0.01, 0.16; p-trend=0.12; - In age ≥70y; ○ Med+EVOO v. Control, β: −0.13, 95% CI: −0.24, −0.02; p-trend=0.02; ○ Med+Nuts v. Control, β: −0.0004, 95% CI: −0.11, 0.11; p-trend=0.95; Summary:; NS/Null: Med+EVOO or Med+Nuts v. Control & Δ Wt, Δ WC (1 y, 3 y, average/y); Significantly lower WC only at 5 y in Med+Nuts v. Control diet | - No adjustment for multiple testing; includes imputed data; Funding: Spanish Government, CIBERobn, Instituto de Salud Carlos III, Hojiblanca, Patrimonio Comunal Olivarero, California Walnut Commission, Borges SA, and Morella Nuts
Georgoulis, 2020; 2021 and 2023 ^113^; Greece; MIMOSA; Analytic N=180; Participant characteristics:; Health: Mean BMI 35.4, 79% Ob; 61% (n=110) fulfilled MS criteria at baseline (most prevalent disorders were increased WC, HTN followed by decreased HDL and increased TG, hyperglycemia); 77% severe OSA; 75% male; low-PA level; Race and/or Ethnicity: NR; SEP: 38% low, 46% medium, 16% high income | Age at Dietary Pattern: 49y, mean (18 to 65 y) at baseline; [underlined: MDG:] high consumption of olive oil, vegetables, legumes, whole grains, fruits and nuts, moderate consumption of poultry, fish and dairy products, low consumption of red meat products and sweets, and low-to-moderate consumption of wine; 7, 60-min group counselling sessions, biweekly for the first two months and monthly for the next four months; based on cognitive behavioral therapy; + CPAP device; [underlined: SCG]: Written advice for a healthy lifestyle and an indicative hypocaloric daily dietary plan, i.e., 7531 kJ (1800 kcal) for men and 6276 kJ (1500 kcal) for women; + CPAP prescription; [underlined: MDG v. SCG] had higher Mediterranean Diet Score (MedDietScore) [Panagiotakos, 2007]: Positive: fruits, vegetables, grains (preferably whole grains), dairy,fish & seafood, white meat, legumes, olive oil. Negative: red meat, processed meat, sugar, salt. Moderate alcohol; Data not included for MLG comparisons due to multicomponents: MDG+physcial activity and optimal sleep duration and quality; + CPAP device; Method(s): RCT/Index | Follow-up duration: 6mo, 12mo; MDG vs. SCG & Obesity at 6mo, RR: 0.23, 95% CI: 0.09, 0.57; p=0.002; BMI, kg/m2; - 6mo: −3.07, 95% CI: −3.93, −2.22, P<0.001; - 12mo: 2.95, 95% CI: −3.89, −2.01, p-trend<0.001; WC; - 6mo: −5.51, 95% CI: −8.50, −2.51, P<0.001; - 12mo: −3.63, 95%CI: −7.12, −0.14, P=0.039; Increased WC; - 6mo: RR 0.68, 95% CI: 0.17, 2.70, P=0.6; P-adj=0.9; - 12mo: RR: 0.98, 95% CI: −.46, 2.10, p-trend=0.863; % ΔWt; - 6mo: −7.4% [4.1] v. 0.3% [3.6], p<0.001; Wt, kg; - 6mo: −8.96, 95% CI: −12.6, −6.33, P<0.001; - 12mo: −8.43, 95% CI: −11.3, −5.54, p-trend<0.001; Summary: Significantly lower risk of obesity and greater reductions in BMI, WC, and Wt @ 6 or 12mo in the MDG v. SCG group; NS: MDG v. SCG & odds of increased WC @ 6 or 12mo | - MDG v. SCG only relevant data for GBCO; No true control/placebo; - High attrition rate (35% for SCG, 29% for the MDG);; - Follow-up times relative to reported results were not clearly reported; - No record of feedback on intervention;; - No adjustment for multiple testing; includes imputed data; SCG did not include CPAP device; - ITT and per-protocol analyses generated similar results in different publications.; - No significant differences were observed between completers (n=127) v. dropouts(n=53) in age, sex, education, financial and employment status, dietary, physical activity and sleep habits, or body weight status, AHI and OSA severity, presence of the MS (all p≥0.1).; - Both intervention arms had high participation rate in the counselling sessions (mean number of attended sessions, MDG: 6.38 ± 0.66, MLG: 6.58±0.62, P=0.2).; Funding: Department of Nutrition and Dietetics, Harokopio University
Gotfredsen, 2021 ^120^; Denmark; Diet and Prevention of Ischemic Heart Disease: a Translational Approach (DIPI); Analytic N=186; Participant characteristics:; Health: 100% with 1 or more risk factors (Ob/OW, BMI 25; WC 80cm/94cm; Physically inactive); - Overweight: 51%, 56%, 51% (HAB, SUB, OFF); - Obesity: 16%, 22%, 21% (HAB, SUB, OFF); Race and/or Ethnicity: 100% Danish (NR); SEP: Education (HAB, SUB, OFF):; - ≤HS, 22%, 26%, 29%;; - Associate 11%, 8%, 6%;; - Undergrad. 37%, 42%, 40%;; - Grad 30%, 24%, 25% | Age at Dietary Pattern: 30 to 65 y at baseline; [underlined: SUB DG group]: Targeted substitution dietary guidance, “Eat fruit instead of candy and cake; Eat coarse vegetables instead of fine vegetables; Eat fish instead of red meat; Eat whole grain products instead of products with no whole grains; Eat unsaturated fat instead of saturated fat”; [underlined: OFF group]: Official Danish dietary guidance, “Eat a variety of foods, but not too much, and be physically active; Eat fruits and many vegetables; Eat more fish; Choose whole grains; Choose lean meats and cold meats; Choose low-fat dairy products; Eat less saturated fat; Eat foods with less salt; Eat less sugar; Drink water”; [underlined: HAB group]: habitual intake (no intervention); Method(s): Other RCT | Follow-up duration: 6mo; SUB v. HAB; - BF% 6mo, β: 0.08, 95% CI: −0.54, 0.70;; - BF% 12mo, β: 0.59, 95% CI: −0.20, 1.38; - Trunk % 6mo, β: 0.12, 95% CI: −0.62, 0.87; - Trunk % 12mo, β: 0.75, 95% CI: −0.16, 1.67; - BMI 6mo, β: −0.13, 95% CI: −0.47, 0.20; - BMI 12mo, β: −0.06, 95% CI: −0.47, 0.35; - WC 6mo, β: −0.29, 95% CI: −1.62, 1.05; - WC 12mo, β: −0.92, 95% CI: −2.33, 0.48; - WHR 6mo, β: 0.003, 95% CI: −0.009, 0.02; - WHR 12mo, β: −0.007, 95% CI: −0.02, 0.005; - Wt 6mo, β: −0.40, 95% CI: −1.40, 0.60; - Wt 12mo, β: −0.19, 95% CI: −1.40, 1.03; OFF v. HAB; - BF% 6mo, β: −0.10, 95% CI: −0.72, 0.5; - BF% 12mo, β: −0.04, 95% CI: −0.82, 0.74; - Trunk % 6mo, β: −0.12, 95% CI: −0.86, 0.62; - Trunk % 12mo, β: −0.03, 95% CI: −0.93, 0.88; - BMI 6mo, β: −0.24, 95% CI: −0.58, 0.09; - BMI 12mo, β: −0.17, 95% CI: −0.58, 0.23; - WC 6mo, β: 0.11, 95% CI: −1.22, 1.45; - WC 12mo, β: −0.08, 95% CI: −1.49, 1.32; - WHR 6mo, β: −0.00009, 95% CI: −0.01, 0.01; - WHR 12mo, β: 0.0008, 95% CI: −0.01, 0.01; - Wt 6mo, β: −0.67, 95% CI: −1.67, 0.32; - Wt 12mo, β: −0.47, 95% CI: −1.68, 0.73; Summary: NS/Null: SUB v. HAB or OFF v. HAB & BF%, Trunk Fat%, BMI, WC, WHR, Wt | - Intervention was not well-controlled (i.e., weak); - Diet assessed at 3 times, 6mo apart; Funding: Danish Council for Strategic Research
Jenkins, 2017 ^124^; Canada;; Analytic N=919; Participant characteristics:; Health: 100% OW; Race and/or Ethnicity: NR; SEP: NR | Age at Dietary Pattern: ≥ 18 y, mean 44.7y; [underlined: Advice]: Increased intake of fruit, vegetables, whole grains, and cereals v. Control arm after 6mo; Advice to increase fruit, vegetables, whole grains, cholesterol-lowering foods (e.g., soy foods, nuts, and viscous fiber sources such as oats and barley and reduce meat, sweets, sugar-sweetened beverages; [underlined: Advice+Food]: Higher intakes of fruit, vegetables, whole grains, nuts, soy protein, and viber than control arm after 6mo; Advice to increase fruit, vegetables, whole grains, cholesterol-lowering foods (e.g., soy foods, nuts, and viscous fiber sources such as oats and barley and reduce meat, sweets, sugar-sweetened beverages; plus provided weekly food basket; [underlined: Food:] Higher intakes of fruit, vegetables, whole grains, nuts, soy protein, and fiber than control arm after 6mo; Provided weekly food basket; [underlined: Control]: Lower intakes of fruits and vegetables after 6mo than three intervention arms; Method(s): RCT | Follow-up duration: 6mo; 18mo; BMI Tx difference (range); - Advice v. Control,; ○ 0 to 6mo: −0.1 (−0.5, 0.2); PR>0.463; ○ 0 to 18mo: −0.1 (−0.7, 0.4); PR>0.601; - Advice+Food v. Food,; ○ 0 to 6mo: −0.2 (−0.6, 0.3); PR>0.469; ○ 0 to 18mo: −0.1 (−0.8, 0.6); PR>0.777; WC Tx difference (range); - Advice v. Control,; ○ 0 to 6mo: −0.7 (−2.2, 0.8); PR>0.339; ○ 0 to 18mo: 0.1 (−1.3, 1.6); PR>0.849; ○ 6 to 18mo: 0.7 (−0.9, 2.3); PR>0.376; - Advice+Food v. Food,; ○ 0 to 6mo: −0.9 (−2.5, 0.7); PR>0.251; ○ 0 to 18mo: −0.4 (−2.4, 1.5); PR>0.658; ○ 6 to 18mo: 0.3 (−1.6, 2.1); PR>0.787; Wt Tx difference (range); - Advice v. Control,; ○ 0 to 6mo: −0.2 (−1.5, 1); PR>0.695; ○ 0 to 18mo: −0.3 (−1.3, 0.7); PR>0.584; ○ 6 to 18mo: −0.1(−1.3, 1.1); PR>0.842; - Advice+Food v. Food:; ○ 0 to 6mo: −0.5 (−1.9, 0.9); PR>0.475; ○ 0 to 18mo: −0.4 (−1.8, 0.9); PR>0.515; ○ 6 to 18mo: −0.1(−1.4, 1.2); PR>0.87; Summary: NS/Null in BMI, WC, Wt | - Greater drop-out rates in arms that did not receive food;; - Greater adverse events in treatment arms than control; Funding: Institute of Nutrition, Metabolism, Diabetes of the Canadian Institute for Health Research, and Loblaw Cos
Lima, 2013 ^139^; Brazil;; Analytic N=206 (156 completed); Participant characteristics:; Health: 100% HTN, mostly Ob; Race and/or Ethnicity: Non-white: 87%; SEP: Income: low, 36% v. 29%, mid 53% v. 55%, high 11% v. 17% | Age at Dietary Pattern: ≥ 20y, mean 44.7y; [underlined: DASH:] Guidance to increase vegetables, fruits, legumes (beans and manioc products), low-fat dairy products, grains, roots and tubers, fish, and avoid excess salt, meats and meat products and SSBs; Reported consumption of vegetables, fruits, beans, milk and dairy foods, fish, and added fats and oils; [underlined: Control]: Guidance to reduce sodium intake; Reported consumption of vegetables, fruits, beans, milk and dairy foods, fish, and added fats and oils; Method(s): RCT | Follow-up duration: 6mo; DASH v. Control & Wt, kg, at:; - 1mo, 65.7 v. 64.5; - 2mo, 65.3 v. 64.4; - 3mo, 65 v. 64.4; - 4mo, 64.7 v. 64.4; - 5mo, 64.3 v. 64.4; - 6mo, 64 v. 64.3; p<0.01; Summary: Significantly lower body weight across 1–6 mo follow-up for DASH diet compared to Control. | - Both groups received anti-HTN meds as Co-Intervention (drug NR); - Dietary intake assessed with 3 non-consecutive 24h records; Funding: Fundaçãs de Amparo e Pesquisa do Estado do Maranhão and Coordenaçãs de Aperfeiçoamento de Pessoal de Nível Superior
Luo, 2022 ^144^; China; n/a; Analytic N=202; Participant characteristics:; Health:; - 100% Prediabetes;; - 100% OW/Ob;; - 18% on lipid/HTN meds; Race and/or Ethnicity: NR (Chinese); SEP: Education: 92% 13y+; 8% 12y or less; | Age at Dietary Pattern: 25 to 60 y; [underlined: Mediterranean Diet (MD)]: ∼25% energy restriction. Positive: extra-virgin olive oil, marine fish, nuts, whole grain products, fruits, vegetables, poultry. Negative: refined cereals, meat, soy products, sunflower oil; [underlined: Traditional Jiangnan Diet (TJD, traditional cuisine of SE China)]: ∼25% energy restriction. Positive: refined cereals, legumes, vegetables, fruits, freshwater fish and shrimp, soy products, sunflower oil. Moderate: whole grains such as brown rice. Negative: meat, poultry, nuts, oil oil; [underlined: Control Diet (CD, current diet of megacities)]: ∼25% energy restriction. Positive: Refined cereals, meat, poultry, sunflower oil, refined rice. Negative: brown rice, buchwheat products, fruits, vegetables, freshwater fish, marine fish, nuts, soy products, olive oil; Method(s): RCT | Follow-up duration: 3mo, 6mo; ΔVAT, 3 mo; - MD, EMM: −34.1, 95% CI: −41.6, −26.50; - TJD, EMM: −30.8, 95% CI: −37.7, −23.9; - CD, EMM: −29.0, 95% CI: −35.7, −22.3; ΔVAT, 6 mo p-trend=0.44; - MD, EMM: −39.88, 95% CI: −47.7, −32.1; - TJD, EMM: −36.2, 95% CI: −43.7, −28.6; - CD, EMM: −40.5, 95% CI: −47.5, −33.5; ΔSAT, 3 mo; - MD, EMM: −22.4, 95% CI: −28.2, −16.6; - TJD, EMM: −15.2, 95% CI: −20.6, −9.90; - CD, EMM: −17.7, 95% CI: −22.9, −12.5; ΔSAT, 6 mo p-trend=0.26; - MD, EMM: −25.8, 95% CI: −31.8, −19.7; - TJD, EMM: −17.7, 95% CI: −23.6, −11.9; - CD, EMM: −24.4, 95% CI: −29.8, −19.0; ΔAbdominal fat, 3 mo; - MD, EMM: −56.6, 95% CI: −68.2, −44.9; - TJD, EMM: −45.8, 95% CI: −56.4, −35.2; - CD, EMM: −47.1, 95% CI: −57.4, −36.7; ΔAbdominal fat, 6 mo p-trend=0.17; - MD, EMM: −65.6, 95% CI: −77.5, −53.6; - TJD, EMM: −53.9, 95% CI: −65.3, −42.5; - CD, EMM: −65.2, 95% CI: −76.0, −54.5; ΔWt (kg), 3 mo; - MD, EMM: −5.11, 95% CI: −5.79, −4.44; - TJD, EMM: −4.72, 95% CI: −5.38, −4.06; - CD, EMM: −4.97, 95% CI: −5.64, −4.31; ΔWt (kg), 6 mo p-trend=0.64; - MD, EMM: −5.72, 95% CI: −6.40, −5.03; - TJD, EMM: −5.05, 95% CI: −5.73, −4.38; - CD, EMM: −5.38, 95% CI: −6.06, −4.70; Summary: NS/Null: ΔWeight, ΔAbdominal Fat, ΔVAT, ΔSAT in MD compared to either TJD or Control [Note that all three groups lost VAT, SAT, WC, and Wt] | All arms were calorie-restricted [lost VAT, SAT, WC, and Wt] and received study foods (i.e., controlled-feeding study); Funding: Strategic Priority CAS Project, Chinese Academy of Sciences, Ministry of Science and Technology of China, National Natural Science Foundation of China, Shanghai Municipal Science and Technology Major Project, Outstanding Academic Leader Project of Shanghai Municipal Health Commission, Shanghai Medicine and Health Development Foundation
Maruyama, 2021 ^145^; Japan; n/a; Analytic N=98; Participant characteristics:; Health: 100% dyslipidemic (43% on LDL-lowering med; 18% TG-lowering med; 28% on both); Race and/or Ethnicity: NR; SEP: NR | Age at Dietary Pattern: 54y, mean; 30 to 65y at baseline; [underlined: Japan Diet (JD)]: Consume more vegetables; seaweed/mushrooms/konjak; unrefined cereals or barley; soybean products - natto; fish; Reduce animal fat/fatty meat/poultry; confections; alcohol; [underlined: Partial JD (PJD)]: Reduce animal fat/fatty meat/poultry; confections; alcohol; Method(s): RCT | Follow-up duration: Δ3mo; Δ6mo; Mean differences (95% CI); BMI,; - 0–3mo: 0.1 (−0.2, 0.4); Effect size: 0.14; p=0.50; - 3–6mo: 0.1 (−0.2, 0.5); Effect size: 0.16; p=0.43; WC,; - 0–3mo: −1.0 (−2.1, 0.0); Effect size: 0.41; p=0.053; - 3–6mo: −1.2 (−2.5, 0.2); Effect size: 0.35; p=0.091; Wt,; - 0–3mo: 0.3 (−0.4, 1.0); Effect size: 0.16; p=0.44; - 3–6mo: 0.4 (−0.6, 1.3); Effect size: 0.17; p=0.41; Summary: NS/Null: BMI, WC and Wt in JD vs. PJD; marginally lower WC only at 0–3mo | Canned mackerel, rice with barley provided to JD arm; Funding: SKYLARK Food Science Institute
Murphy, 2022 ^153^; Australia; MedLey; Analytic N=108; All non-smokers, w/o chronic disease and major psychological illnesses; Participant characteristics:; Health: NR; Race and/or Ethnicity: NR; SEP: NR | Age at Dietary Pattern: 71 y, mean; 64 to 86 y at baseline; modified Mediterranean Diet Score (MedDiet) [Davis 2017 modifed Sofi, 2008]; [underlined: MedDiet group:] higher MedDiet scores than Control group, Positive: Vegetables; Fruit; Nuts; Legumes; Whole grains; Olive Oil. Negative: Potatoes (White, starchy); Dairy (whole or low-fat; products); Eggs; Red meat; Sugars; Discretionary Foods; Other Alcohol; Moderate: Fish; Red wine; Control group consumed less EVOO, vegetables, fish, more discretionary foods; Method(s): RCT/Index/Score analysis | Follow-up duration: 6 to 18mo; ΔBMI, kg/m2, mean difference; - 6 to 18mo: MedDiet, Mean: 0.1±0.1, 95% CI: −0.2, 0.3; p-trend=0.498 vs. Control, Mean: 0.1±0.1, 95% CI: −0.2, 0.4; p-trend=1.000; MedDiet vs. Control, p-trend=0.049; - 0 to 18mo: MedDiet, Mean: −0.2±0.1, 95% CI: −0.5, 0.2; p-trend=1.000; ΔWt (kg), mean difference 6 to 18mo; - 6 to 18 mo, MedDiet, Mean: 0.2±0.3, 95% CI: −0.6, 0.9; p-trend=0.387 vs. Control, Mean:0.1±0.3, 95% CI: −0.6, 0.9; p-trend=1.000; MedDiet vs. Control, p-trend=0.019; - 0 to 18mo, MedDiet, Mean: −0.4±0.3, 95% CI: −1.3, 0.5; p-trend=1.000; Summary: NS/Null: MedDiet scores & ΔBMI or ΔWt from 6–18mo | - Diet repeatedly assessed with 74-item validated FFQ; Authors did not consider between-group differences as significant; - Funding: None (Primary intervention study funded by National Health and Medical Research Council of Australia)
Pattinson, 2020 ^156^; Australia; TEMPO; Analytic N=79; Participant characteristics:; Health: 100% Ob women postmenopause; Race and/or Ethnicity: NR, “Predominantly White”; SEP: NR (all from metro area) | Age at Dietary Pattern: 45 to 65 y at baseline; [underlined: Food-Based (FB) Group]: Increased intake of Fruit, decreased intake of Discretionary Foods vs.TMR; Assigned to 3–6 serv/d protein foods (meat and meat alternatives, reduced-fat dairy); 4 serv/d CHO foods (grains, cereals, starchy vegetables); 2 serv/d fruits; 5 serv/d non-starchy vegetables; 2 serv/d fats; up to 1 serv/d discretionary food and/or alcohol;; [underlined: Total Meal Replacement (TMR) Group]: Decreased intake of Fruit, Increased intake of Discretionary Foods vs. FBG; Assigned to 65–75% energy restriction for 16 wks. Included 3 MR shakes or soups, up to 2 c/d non-starchy vegetables, 1 tsp/d fats or oils. Minimal-energy foods such as diet jelly, black tea and coffee, garlic, herbs and spices permitted. 16-wk period followed by moderately energy-restricted food-based diet;; [underlined: Healthy Eating Index for Australian Adults (HEIFA) [Pattinson, 2021 modified Roy 2016]]: Positive: Vegetables; Vegetable variety; Fruit; Fruit variety; Total Grains; Whole grains; Fat (PUFA foods, US oils, nuts, seeds). Negative: Saturated Fat; Added Sugars; Discretionary Foods (including processed meat). Moderate: Dairy and Dairy Alternatives; Meat and Meat Alternatives (not processed); Method(s): RCT/Index/score | Follow-up duration or age: 52 wks; PP, mean difference ΔWt (kg); - TMR v. FBG, −6.5, 95% CI: −9.4, −3.6; p-trend<0.001; - ΔHEIFA, −8.2, 95% CI: −13.8, −2.7; p-trend=0.004; ITT, mean difference ΔWt (kg); - TMR v. FBG, −7.4, 95% CI: −10.3, −4.4; p-trend<0.001; - ΔHEIFA, −5.1, 95% CI: −9.7, −0.5; p-trend=0.030; Summary: Significantly greater Wt loss (∼ 1.7× more) at 52 wk between those in the Food-based group (FBG), with higher HEIFA scores, compared to the total meal replacement (TMR) group | - Unequal provision of food between interventions (only meal replacements given);; - Advice offered to participants after transitioning off meal-replacements;; - HEIFA was not designed specifically for weight loss; Funding: National Health and Medical Research Council of Australia; University of Sydney; Australian Government Department of Education and Training
Pavic, 2019 ^157^; Croatia; Other:; Analytic N=124; Participant characteristics:; Health: 100% Ob/OW; Race and/or Ethnicity: NR; SEP: Education: 42% v. 27% uni+; Employment: 59% v. 37%; Married: 67.2% v. 67.2% | Age at Dietary Pattern: 18 to 69 y; [underlined: Mediterranean diet (MD):] Increased intake (but NS) of olive oil, nuts, and fish vs. SHD; Assigned to nutrition education, behavior therapy, exercise, and MD: vegetables (2–3 servings/day), fresh fruits (3 servings/day), whole grains (e.g. non-refined cereals, whole-grain bread, pasta etc.), non-fat or low-fat dairy products (1–2 servings/day); low in red meat, with poultry and fish (3–4 servings/week) replacing pork, beef and lamb; energy intake restricted to an average of 1573 kcal/d; 3–4 portions of fish per wk, nuts handful/d (56 g/wk) and 2 tablespoons (corresponding to 30 ml) of EVOO/d provided at the study entry.; [underlined: Standard Hypolipidemic Diet (SHD)]: Lower but NS in olive oil, nuts, and fish vs. MD; Assigned to nutrition education, behavior therapy, exercise, and SHD: whole grains, fruit (3 servings/d), vegetables (2–3 servings/d), restricted additional fats, sweets and high-fat snacks with energy intake limited to 1287 kcal/day; recommended non-fat or low-fat dairy products (1–2 servings/d), legumes (4 servings/wk); Encouraged fish if already part of a regular diet but <1/weekly; Reduce salt; Method(s): RCT | Follow-up duration or age:12mo; MD vs. SHD, mean [SD] Δ 0–12mo; - ΔBMI, kg/m2: −3.0 [3.2] vs. −1.8 [2.9]; P<0.001; - ΔWC, cm: −7.7 [7.3] vs. −5.1 [6.6], P<0.001; - ΔWt, kg: −8.7 [9.6] vs. −4.9 [8.1], P<0.001; Summary: Significantly greater reductions in BMI, WC, and Wt over 12mo in the MD compared to SHD | - Drop-out rate: 33.1% (motivation and/or unwillingness to continue, health related issues, pregnancy, death and unknown); - Adherence to diet was reported as “satisfactory” but MD v. SHD did not significantly differ in the increase intake in olive oil, nuts, fish and reduced red or processed meats, sweets, sweetened beverages and alcoholic drinks; - All participants intervened upon with diet, physical activity and supervision therefore the results represent interaction effect of all three components; Funding: NR
Poulsen, 2015 ^159^; Denmark;; Analytic N=147 (110 completed); Participant characteristics:; Health: 43–45% MetSyn; mean BMI 30.7; 80–88% HTN and 13% on HTN-meds; Race and/or Ethnicity: NR; SEP: NR | Age at Dietary Pattern: 43y, mean at baseline; [underlined: New Nordic diet (NND), controlled feeding intervention]: Vegetables (cabbages, root, legumes); Fruit (berries); Potatoes; Nuts, Whole grain; Meat (game); Fish and shellfish; Seaweed; Wild plants and mushrooms; Fresh herbs; [underlined: Average Danish Diet (ADD):] NR; Method(s): RCT | Follow-up duration or age:12mo; NND v. ADD, adjused mean differences; @ 26 wks; - WC: −3.5, 95% CI: −5.6, −1.4; p=0.002; - Hip: −2.1, 95% CI: −3.8, −0.5; p=0.01; - Sagittal diameter: −0.9, 95% CI: −1.5, −0.2; p=0.008; - Wt:−3.3, 95% CI: −5.0, −1.6; p<0.001; @ 78 wks; - WC: 1.7, 95% CI: −0.3, 3.6; p=0.1; - Hip-C: 2.4, 95% CI: 0.7, 4.2; p=0.006; - Sagittal diameter: 0.6, 95% CI: 0.0, 1.2; p=0.07; - Wt: 1.8, 95% CI: 0.1, 3.4; p=0.041; Summary: Significantly greater weight loss and lower WC, Hip-C, and Sagittal diameter at 26 weeks NND v. ADD. However, NND v. ADD+NND regained more Wt, Hip-C at 78 weeks; NS: Both NND and ADD+NND regained WC and Sagittal diameter at 78 wk. | Dietary compliance was partially subjective; Funding: Nordea Foundation Denmark
Reidlinger, 2015 ^162^; United Kingdom; Cardiovascular disease risk REduction Study (CRESSIDA); Analytic N=162; Participant characteristics:; Health:; - Non-smoking, healthy;; - Mean BMI 25.5 v. 26.8;; - mean WC 98 v. 97 cm;; - 50% v. 56% postmenopausal; Race and/or Ethnicity: DG v. CG; - White: 87% v. 80%; - Black: 7% v. 8%; - Asian: 7% v. 8%; SEP: NR | Age at Dietary Pattern: 40 to 70 y; [underlined: “Dietary Guidelines” DG diet]: Increased Vegetables and Fruit; Whole Grains; Oily Fish; Reduced Total Fat; SFA; Sodium; Added Sugars; Advice to choose Low-fat Dairy; Lean Meat; and Limit Meat; Meat products, SSBs; Salt; Confectionary, Snacks; Moderate alcohol; [underlined: Control]: traditional British diet without sugar/salt restrictions: Higher in Refined Cereals; Potatoes; Meat; Moderate in Whole Grains, Oily Fish; Advice to consume Vegetables, Fruit, Full-Fat Dairy and Limit Confectionary, snacks; Moderate alcohol; Method(s): RCT | Follow-up duration or age: 12 wks; WC, −1.7, 95% CI: −2.8, −0.7; p=0.002; Wt, kg, −1.9%, 95% CI: 2.5,−1.3; p<0.001; Summary: Significantly lower weight and WC at 12 wk in those on DG diet v. Control | Advised both groups in attempt to keep weight stable; Funding: UK Food Standards Agency and Department of Health and by the National Institute for Health Research (NIHR) Clinical Research Facility at Guy’s and St Thomas’ NHS Foundation Trust and NIHR Biomedical Research Centre based at Guy’s and St Thomas’ NHS Foundation Trust and King’s College London
Sidahmed, 2014 ^169^; United States; Healthy Eating for Colon Cancer Prevention Study; Analytic N=120; Participant characteristics:; Health: 64% family Hx of CRC, 27% Hx adenoma, or 9% both; Race and/or Ethnicity: 88% Caucasian; SEP: NR | Age at Dietary Pattern: 53 y, mean at baseline; [underlined: ‘Healthy eating’ arm]: Assigned to consume Fruit 2 serv/d, Vegetables 2 serv/d, Dark green or orange vegetables 1 serv/d, Whole grains ≥3 serv/d, SFA <10% Total E; [underlined: ‘Mediterranean’ arm:] Assigned to consume Fruit (vit. C) 1 serv/d, Fruit (Other) 1 serv/d, Allium vegetables 1–2 serv/d, Dark green vegetables 1–2 serv/d, Orange and yellow vegetables 1–2 serv/d, Red vegetables 1–2 serv/d, Other vegetables 1–2 serv/d, Dark green herbs 1 serv/d, Whole grains ≥3 serv/d, High MUFA foods 7–10 exchanges/d, High n-3 foods 3 oz, twice/wk; Method(s): RCT | Follow-up duration or age: 6mo; Hip circumference: Mediterranean 41.1 to 40.0 inches; data NR for ‘Healthy Eating’ arm; Healthy v. Mediterranean and Wt. loss: 0.92 kg v. 1.58 kg, NS;; Within Mediterranean arm, those who were OW/Ob lost significantly more weight than those who were not.; Summary: NS/Null: ‘Healthy eating’ v. ‘Mediterranean’ diet groups did not differ in weight loss | Compliance with assigned intervention was difficult to interpret and low at 6 mo: Healthy 67% v. Mediterranean 32% compliant with meeting 100% of dietary goals; Healthy 89% v. Mediterranean 85% compliant with meeting ≥70% of dietary goals; Funding: NIH; Cancer Center Support
Turner-McGrievy, 2015 ^174^; United States;; Analytic N=62 (power estimate of 80% for n=12 per arm); Participant characteristics:; Health: mean BMI ∼33–36; Race and/or Ethnicity: 18% Black; 81% White; 1% Other; SEP: 94% of participants were college graduates or held advanced degrees; 63% married | Age at Dietary Pattern: 43 to 53y, mean across groups; [underlined: Vegan:] No animal products (meat, fish, poultry, eggs, or dairy) but emphasizes plant-based foods, such as fruits, vegetables, whole grains, and legumes/beans.; [underlined: Vegetarian:] No meat, fish, or poultry but does contain eggs and dairy, in addition to plant-based foods, such as fruits, vegetables, whole grains, and legumes/beans.; [underlined: Pesco-vegetarian]: No meat or poultry but does contain fish and shellfish, eggs, and dairy, in addition to plant-based foods, such as fruits, vegetables, whole grains, and legumes/beans.; [underlined: Semi-vegetarian]: All foods, including meat but red meat 1/wk, poultry 5/wk, fish and shellfish, eggs, and dairy, in addition to plant-based foods, such as fruits, vegetables, whole grains, and legumes/beans.; Omnivore: All food groups; Method(s): RCT | Follow-up duration or age:6mo; WL at 6mo; - Vegan v. Omni: −7.5% (4.5%) v. −3.1% (3.6%); P 0.03; - Vegan v. Semi-Veg: −7.5% (4.5%) v. −3.2% (3.8%); P 0.03; - Vegan v. Pesco-Veg: −7.5% (4.5%) v. −3.2% (3.4%); P 0.03; Summary: Greater weight lost at 2mo in each dietary pattern compared to Omnivore; Greater weight lost at 6mo in the Vegan and Vegetarian groups compared to other patterns; Those in any arm lost weight at 2mo and 6mo | - Analyses were not powered to detect differences between diets or weight loss, despite power estimate at n=12 per arm;; - Sample was mostly White, educated, men; - Unclear reporting of data on weight for all arms and time points; Funding: NR
Tussing-Humphreys, 2022 ^175^; United States; Building Research in Diet and Cognition study; Analytic N=100; Participant characteristics:; Health:; - 100% OW/Ob; 67% HTN; Race and/or Ethnicity:; - 91% non-Hispanic, Black; - 3% Native American; - 6% Multi-racial; SEP:; - Income: 22% <$20K, 23% $20-$40K, 54% >$40K; 99% health-insured; - Education: 30% grad. degree; 20% college grad; 10% associate degree; 9% ≤HS; - Marital status: 25% single; 28% married; 16% widowed; 31% divorced | Age at Dietary Pattern: 55 to 85 y at baseline; [underlined: MedDiet Score (MDS) [Tangney 2011]:] Positive: Non-refined arains, potatoes, fruit, vegetables, legumes and nuts, fish, olive oil. Negative: Red meats, poultry, full-fat dairy. Moderate: wine, alcohol; [underlined: MedDiet Group:] Higher MDS v. Control at 8mo F/U; Assigned to follow MDS recommendations, maintain body Wt and PA; Increased MDS by F/U; [underlined: Control Group]: No dietary recommendation provided; Health education materials provided weekly. No change in MDS by F/U, but lower MDS than MedDiet at F/U; Method(s): Index, RCT | Follow-up duration or age: 8mo; MedDiet vs. Control; Δ%BF, mean: −0.8, 95% CI: −1.2, −0.3 vs. −0.2, 95% CI: −0.8, 0.4; p-trend=0.02; ΔBMI, mean: −1.0, 95% CI: −1.4, −0.6 vs. −0.2, 95% CI: −0.8, 0.3; p-trend<0.001; ΔVisceral Adipose Mass, mean: −162, 95% CI: −248, −76 vs. 91, 95% CI: −18, 200; p-trend<0.001; ΔWt (kg), mean: −2.6, 95% CI: −3.7, −1.5 vs. −0.6, 95% CI: −2.1, 0.8; p-trend<0.001; Summary: Significantly greater reductions in weight, BMI, BF%, and Visceral Adipose Mass in MedDiet v. Control groups | MedDiet+ER group data not included here due to it reflecting multi-components; Funding: NIH
Van Horn, 2020 ^177^; United States; WHI; Analytic N=10371; Participant characteristics:; Health: BMI, mean 28; 2% treated for DM; 100% normotensive; Race and/or Ethnicity:; - White: 84–85%;; - Black 7–8%;; - Hispanic: 3–4%;; - American Indian/Alaska Native: 0.3%;; - Asian/Pacific Islander ∼2%;; - Unknown 1–2%; SEP: NR | Age at Dietary Pattern: 61 y, mean at baseline; [underlined: Intervention v. usual diet]: increased vegetables, fruit, grains, and reduced fat; Higher aMED (higher legumes separate from nuts), DASH, aHEI-2010, and HEI-2005 (higher low-fat dairy) scores after 1y; - Alternate Med Diet Score (aMED) [Fung 2005]; - DASH Score [Fung 2008]; - Alternative HEI (AHEI)-2010 [Chiuve 2012]; - Healthy Eating Index (HEI-2005) [Guenther 2008]:; Method(s): RCT/Index/score | Follow-up duration or age: 1y; WC (cm): −2.0 ± 6.6 vs. −0.1 ± 6.6, p<0.001; Wt (kg): −2.4 ± 7.7 vs. 0.2 ± 8.8, p<0.001; Summary: Increased scores for aMED, AHEI-2010, HEI-2005, and DASH was significantly associated with lower weight and WC after 1y | - Attempted to titrate TEI in order to maintain weight between groups. Both intervention and control groups lost weight; - Adherence to intervention confirmed with higher scores on multiple indices; Funding: NR

a Abbreviations: DM, Diabetes; HS, high school; HTN, hypertension; NR, not reported; Ob, Obesity; OW, Overweight; SEP/SES, Socioeconomic position/status

a Abbreviations in Results: BF, Body fat (total unless specified as trunk, gynoid, android, etc.); BF%, Body fat percentage; FFM, Fat-free mass; FFMI, Fat-free mass index; FM, Fat mass (total, unless specified as trunk, gynoid, android, etc.); FMI, Fat mass index; F/U, Follow-up; Hip-C, hip circumference; ITT, intent-to-treat; NR, not reported; NS, not statistically significant; PP, per-protocol; WC, waist circumference; WHR, waist-hip ratio; Wt, Body weight

Table 15 Risk of bias for randomized controlled trials examining dietary patterns consumed by adults and older adults and body composition and risk of obesity^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Deviations from intended interventions (per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall
Alvarez-Perez, 2016 ^81^ | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Arjmand, 2022 ^85^ | LOW | n/a | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Bruno, 2020 ^93^ | SOME CONCERNS | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Calvo-Malvar, 2021 A ^94^ | LOW | LOW | SOME CONCERNS | LOW | LOW | HIGH | SOME CONCERNS
Calvo-Malvar, 2021 B ^95^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | LOW | HIGH | HIGH
Casas, 2022 ^98^ | SOME CONCERNS | n/a | SOME CONCERNS | LOW | LOW | SOME CONCERNS | HIGH
Crosby, 2022 ^104^ | HIGH | LOW | n/a | LOW | LOW | SOME CONCERNS | HIGH
Davis, 2017 J Nutr ^106^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Estruch, 2019 ^108^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Georgoulis, 2020; 2021 and 2023 ^113^ | LOW | SOME CONCERNS | n/a | LOW | LOW | HIGH | HIGH
Gotfredsen, 2021 ^120^ | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Jenkins, 2017 ^124^ | LOW | SOME CONCERNS | n/a | SOME CONCERNS | LOW | HIGH | HIGH
Lima, 2013 ^139^ | LOW | SOME CONCERNS | n/a | LOW | LOW | LOW | SOME CONCERNS
Luo, 2022 ^144^ | LOW | LOW | n/a | LOW | LOW | HIGH | SOME CONCERNS
Maruyama, 2021 ^145^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Murphy, 2022 ^153^ | SOME CONCERNS | LOW | n/a | HIGH | LOW | HIGH | HIGH
Pattinson, 2020 ^156^ | SOME CONCERNS | LOW | n/a | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Pavić, 2019 ^157^ | LOW | n/a | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Poulsen, 2015 ^159^ | HIGH | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | HIGH
Reidlinger, 2015 ^162^ | LOW | LOW | LOW | LOW | LOW | LOW | LOW
Sidahmed, 2014 ^169^ | LOW | LOW | LOW | LOW | LOW | HIGH | HIGH
Turner-McGrievy, 2015 ^174^ | LOW | SOME CONCERNS | n/a | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Tussing-Humphreys, 2022 ^175^ | SOME CONCERNS | LOW | LOW | LOW | LOW | HIGH | HIGH
Van Horn, 2020 ^177^ | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ . RoB 2: a revised tool for assessing risk of bias in randomised trials. BMJ 2019; 366: l4898 31462531 .

Table 16 Evidence in adults and older adults from observational studies examining the relationship between dietary patterns consumed and body composition and risk of obesity^a^

Study Characteristics | Intervention/exposure and comparator | Results | Methodological considerations
Aljadani, 2020_F ^79^; Australia; Australian Longitudinal study on Women’s Health (ALSWH); Analytic N=4083; Participant characteristics:; - Smoking Status: 58% nonsmoker, 18% ex-smoker, 24% smoker; - PA (METs. minutes): 1178.5 ± 1407.2; - ARFS tertiles differed by PA and smoking (at baseline and F/U); Race and/or Ethnicity: NR; SEP:; - Education: 1% no formal school, 28% school certificate, 24% trade and apprentice, 47% university degree and higher; - Marital status: 38% married, 21% defacto, 3% separated, 1% divorced, 0% widowed, 37% single; - Residence: 60% urban, 36% rural, 3% remote | Age at Dietary Pattern: 27–31 y at baseline; Austrailian Recommended Food Behavior Score (ARFS) [Collins, 2008], Positive: Vegetables; Fruit; Grains; Protein foods (Nuts, Beans, Soya; Egg; Fish). Negative: Meat; Neutral: Fat; Alcohol; Method(s): Index/score analysis | Follow-up duration or age:6 y; [underlined: Body weight:]; ARFS & ΔWt (kg); T1, 4.1 ± 6.8 kg; T2, 3.6 ± 6.5 kg; T3, 3.7 ± 6.8 kg; p-trend=0.04; ARFS per 1 pt, β: −0.04, 95% CI: −0.07, 0.00; R2 : 0.03; p-trend=0.03 | - Did not account for: Race/Ethnicity; - Self-reported Wt, Ht used at both baseline and follow-up; - Diet assessed at baseline only; Funding: N/A
Aljadani, 2020_I ^78^; Australia; Australian Longitudinal study on Women’s Health (ALSWH); Analytic N=1999; Participant characteristics:; Race and/or Ethnicity: NR; SEP:; - No education 18%; - School certificate 32%; - Trade, apprenticeship 17%;; - ≥ University degree 23%; Married 77%; Defacto 6%; Separated 3%; Divorced 8%; Widowed 3%; Single 3% | Age at Dietary Pattern: 45 to 49 y at baseline; Austrailian Recommended Food Behavior Score (ARFS) [Collins, 2008, Positive: Vegetables, Fruit, Protein foods (≤2 eggs/wk; ≥1 serving/wk plant protein); Grains; Dairy, Skim or Reduced fat; Negative: Meat (1–4 servings/wk beef, lamb, pork, poultry, fish/seafood); Neutral: PUFA or MUFA margarine; Alcohol; Method(s): Index/score analysis | Follow-up duration or age: 9 y; [underlined: Body weight:]; ARFS & Wt; T1, β=1, ref; T2, β: −0.33, 95% CI: −1.28, −0.62; p=0.49; T3, β: −1.2, 95% CI: −2.31, −0.11; p=0.03 | - [underlined: Did not account for:] Age, Race/Ethnicity, Physical activity; - Self-reported Wt, Ht; Diet assessed over time at Survey 3 (2001) and 6 (2010) with validated, 74-item FFQ; Funding: None
Allaire, 2020 ^80^; United States; Diabetes Prevention Program (DPP); Analytic N=2914; Participant characteristics:; - Participants at high risk of T2D; - Current smoker: 6.2%; Family Hx of T2D: 69.3%; HTN: 28.6%; - BMI kg/m2: 33.9 ± 6.6; - Waist cm: 105.1 ± 14.4; - WHR: 0.92 ± 0.09; - No differences by treamtent group for baseline characteristics; Race and/or Ethnicity: 45% of minority race/ethnicity; 55.4% Caucasian; 19.4% African American, 15.8% Hispanic, 5.3% American Indian, and 4.2% Asian; SEP: Education: 14.8 ± 3.1, no differences by treatment group | Age at Dietary Pattern: ≥25 y at baseline; Alternative HEI (AHEI)-2010 [Chiuve 2012] AHEI-2010, Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains (*this was classifed as high fiber grains and breads); Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:1 y; T2D 3.2y; [underlined: Body weight:]; ΔAHEI & ΔWt, per 10pt β: −0.512 (0.155), p=0.001; Caucasian: β: −1.128 (0.191), p<0.0001; African American: β: −0.363 (0.293), p=0.216; Hispanic: β: −0.852 (0.287), p=0.003; American Indian: β: −0.901 (0.631), p=0.155; Asian: β: 0.494 (0.461), p=0.286; P-interaction=0.020; ΔAHEI & ΔWt, β (SE); Q1, β: 1, ref; Q2, β: −0.401 (0.331), p=0.2264; Q3, β: −0.404 (0.342), p=0.2378; Q4, β: −1.328 (0.347), p=0.0001; Q5, β: −2.357 (0.359), p<0.0001; ΔAHEI & ΔWt over 3.2 y F/U, β: −0.597 (0.070), p<0.0001; Caucasian, β: −0.688 (0.110), p<0.0001; African American, β: −0.324 (0.127), p=0.0108; Hispanic, β: −0.856 (0.139), p<0.0001; American Indian, β: −0.103 (0.242), p=0.6716; Asian, β: −0.158 (0.1652), p=0.3408 | - [underlined: Did not account for:] N/A; - Diet change assessed Δ1y; Wt measured in duplicate; Funding: NIDDK; The General Clinical Research Center Program; National Center for Research Resources; VA; NICHD; NIA; National Eye Institute; NHLBI; NCI; ORWH; the National Institute on Minority Health and Health Disparities; CDC; ADA; Merck KGaA; donated materials from Bristol-Myers Squibb; Parke-Davis; and LifeScan Inc. LifeScan Inc.; Health O Meter; Hoechst Marion Roussel, Inc.; Merck-Medco; Managed Care, Inc.; Merck and Co.; Nike Sports Marketing; Slim Fast Foods Co.; and Quaker Oats Co.; McKesson BioServices Corp.; Matthews Media Group; and the Henry M. Jackson Foundation
Andre, 2020 ^82^; United Kingdom; BIOBANK; Analytic N=21585; Participant characteristics:; - Baseline differences in meds & comorbidities (p<0.0001) between those w/ & w/o incident T2D; Race and/or Ethnicity: NR; SEP: Baseline education level (college or university) differed between those who developed T2D and those who didn’t (p<0.0001)- Incident T2D: 51% college or university; non-incident T2D 39% college or university | Age at Dietary Pattern: 40–69 y at baseline (mean 56.5 y); literature Mediterranean Diet Score (LitMDS) [Sofi 2014], Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish; Olive Oil. Negative: Meat; Dairy Products. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age: 6.1 y, mean F/U; [underlined: Risk of Ob/OW:]; Path α (litMDS→ overweight); HR: 0.92, 95% CI: 0.91,0.93; p-trend<0.0001 | - [underlined: Did not account for:] Age (all T2D models); Race/Ethnicity; Anthropometry at baseline (OW at f/u in mediation analyses); - Diet assessed repeatedly over F/U with 24h-recalls, dietary patterns from ‘latter’ surveys with stable intakes; 10% of whole association between litMDS & T2D was mediated by the reduced overweight associated with each additional point of the Medi diet score, and 4% was due to direct effect of the litMDS on T2D; Funding: Joint Programming Initiative (JPI) Healthy Diet for Healthy Life (HDHL); French National Research Agency; Research Council for Biotechnology and Biological Sciences (UK); Ministry of Economy and Competitiveness (Spain)
Angulo, 2021 ^83^; Mexico; Mexican Teachers’ Cohort; Analytic N=8967 ΔWt; N=7588; WC; Participant characteristics:; - Baseline BMI (kg/m2): 26.8.9 ± 4.3; - 63% of sample overweight or obese at baseline; - Smokers 5.7%, alcohol drinkers 53.4%; - Compared with women with the largest decrease in GDQS, women with the largest increase in GDQS were more likely to be obese and less likely to be in the highest physical activity categories at baseline and were more likely to remain nonsmokers and nondrinkers in 2008; Race and/or Ethnicity: NR; SEP:; - Education at f/u: None ∼2%, HS or less 7–8%, undergrad degree ∼80%, grad degree or above 9–13%;; - Marital status, baseline: ∼14–16% single, ∼9–11% living together, 65% married, ∼9% separated, ∼1–2% widow; - Health insurance, baseline: ∼78% public, 17–21% private, ∼3% other;; - Household assets, baseline: Lowest ∼38–46%; Medium ∼33–37%; Highest ∼21–26% | Age at Dietary Pattern: 25 to 49 y (mean, 41.4 y) at baseline; modified Global Diet Quality Score (GDQS) [Bromage, 2021], Positive: citrus fruits, deep orange fruits, other fruits, dark green leafy vegetables, cruciferous vegetables, deep orange vegetables, other vegetables, deep orange tubers, legumes, nuts and seeds, whole grains, liquid oils, fish and shellfish poultry and game meat, low fat dairy, and eggs; Negative: High-fat Dairy; Red meat; Processed meat; Refined grains and baked goods; Sweets and ice cream; SSBs; Juice; White roots and tubers; Purchased deep fried foods; alternative Healthy Eating Index (AHEI-2010) [Chiuve, 2012], Positive: Vegetables (not potatoes, French fries); Legumes and Nuts; Fruits; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA; Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans-fat; Sodium; Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age: 2 y; [underlined: Body weight:]; Δ GDQS & Δ Wt; Largest decrease, β:0.50, 95% CI: 0.19, 0.81; Small decrease, β: 0.33, 95% CI: 0.09, 0.57; Ref, β: 0, ref; Small increase, β: −0.43, 95% CI: −0.67, −0.20; Largest increase, β: −0.81,95% CI: −1.11, −0.51; p-trend<0.0001; per-SD, β: −0.28, 95% CI: −0.40, 0.16; per-SD, aAHEI-2010, β: −0.18, 95% CI: −0.31, −0.05, Wald test=0.383; [underlined: Waist/Central:]; Δ GDQS & WC Δ; Largest decrease, =β:0.71,95% CI: 0.09, 1.32; Small decrease, β: 0.32, 95% CI: −0.12, 0.77; Ref, β: 0, ref; Small increase, β: −0.49, 95% CI: −0.94, −0.04; Largest increase, β: −1.05, 95% CI: −1.62, −0.48; p-trend<0.0001; per-SD, β: −0.54, 95% CI: −0.78, −0.31; per-SD, aAHEI-2010, β: 0.04, 95% CI: −0.20, −0.30, Wald test=0.006 | - [underlined: Did not account for:] Race/Ethnicity (100% Mexican-Heritage); - Self-reported Wt; Diet change assessed Δ2; Sensitivity analyses showed largest increases in GDQS scores from only positively-scored foods were associated with less Wt and WC gain; whereas the largest decreases in only postive/healthy foods were not (null); largest decreases in GDQS scores from only negatively-scored foods were associated with more Wt and WC gain; Funding: FHI Solutions
Arabshahi, 2017 ^84^; Australia; Nambour Skin Cancer Study; Analytic N=1186; Participant characteristics:; - ∼26–35% OW; ∼14–21% Ob; ∼40–59% with a medical condition; - ∼7–13% current smoker, ∼23–26% former smoker; - Recreational PA (MET-h/wk): ∼29–39% none, ∼20–27% ≤ 4.3, ∼19–24% > 4.3 and ≤ 11.3, ∼13–29% > 11.3; - Differences in baseline BMI, smoking status (♂), medical conditions by tertile of meat-and-fat pattern in women and fruit-vegetable pattern in ♀, and PA in ♀: In T3, ♂ more likely to be current smokers and less likely to have a medical condition. In T3, ♀ were more likely to engage in recreational PA and have a medical condition; Race and/or Ethnicity: 99.7% Caucasian descent; SEP:; - Education: ∼37–44% <grade 12, ∼12–17% certificate/diploma, ∼32–42% trade/apprenticeship, ∼4–12% >bachelor or higher, ∼29–38% professional occupation. | Age at Dietary Pattern: 25 to 75 y at baseline; - “Fruit/vegetable”: High Positive loadings for reduced-fat dairy products, fruit, vegetables, beans and legumes, chicken without skin, fish/seafood, organ meats, wholemeal bread and whole grains, breakfast cereal, cereal products, salad dressing (both women and men); and low intakes of discretionary fat, chiken with skin, and white bread and refined grains (women only); - “Meat/fat”: High Positive loadings for high-fat dairy products, discretionary fat, hot chips, fried eggs, chicken with skin, meat, processed meat, white bread and refined grains, pizza, and salty snacks (both men and women); and very low factor loadings for reduced-fat dairy products, herbal tea (women only), fruit, beans and legumes, chicken without skin, wholemeal bread and whole grains, and breakfast cereal (men only); Method(s): Factor/Cluster: PCA | Follow-up duration or age:15 y; [underlined: Body weight:]; Wt Δ, kg; ‘Meat and Fat’: ♀; T1: 4.1, 95%CI: 1.5, 6.8; T2: 5.0, 95%CI: 2.3, 7.6; T3: 5.2, 95%CI: 2.4, 8.0; P-trend=0.4; ‘Meat Fat’ ♂:; T1: 2.3, 95%CI: −2.6, 7.1; T2: 3.3, 95%CI: −1.6, 8.2; T3: 4.8, 95%CI: −0.1, 9.7; P-trend=0.02; ‘Fruit and vegetable’, ♀:; T1: 5.7, 95%CI: 2.4, 9.0; T2: 3.7, 95%CI: 0.4, 6.9; T3: 5.0, 95%CI: 2.0, 8.0; P-trend=0.5; ‘Fruit and vegetable’, ♂:; T1: 5.4, 95%CI: 0.3, 10.4; T2: 3.5, 95%CI: −1.5, 8.4; T3: 2.9, 95%CI: −2.0, 7.8; P-trend=0.02 | - [underlined: Did not account for:] Smoking (men); Medical conditions (women); - Diet assessed only once at baseline - or only baseline diet data was used for analysis; Funding: National Health and Medical Research Council of Australia; PHRDC
Baldwin, 2020 ^86^; Australia; Australian Longitudinal Study on Women’s Health (ALSWH); Analytic N=8161; Participant characteristics:; - Ov: 32% (34% F/U), Ob: 24% (30% F/U); - General baseline health: Poor: 1.6%; Fair: 12.4%; Good: 39.0%; Excellent/Very Good: 47.1%; Race and/or Ethnicity: NR; SEP:; - SEIFA, mean (SD): at baseline 995.5 (57.5); at F/U 998.2 (85.5); - ARIA (baseline-f/u) Major cities: 34–38%; Inner/Outer Regional: 62–59%; Remote/Very remote: 4–3%; - Ability to manage on current income (baseline): Difficult/Impossible: 39%, f/u 32%; Not too | Age at Dietary Pattern: 52.1 +/− 1.5 y, mean at survey 3 (baseline); Austrailian Recommended Food Behavior Score (ARFS) [Collins, 2008], Positive: Vegetables; Fruit; Grains; Protein foods (Nuts, Beans, Soy, Egg; Fish); Dairy (Reduced-fat/Skim milk; Low-fat cheese). Negative: Meat. Neutral: Fats (PUFA, MUFA, Non-Fat); Alcohol; Method(s): Index/score analysis | Follow-up duration or age:12 y, mean age ∼ 64.3 y; [underlined: BMI:]; ‘diet quality got worse’, n=2361: Mean BMI, 26.9±5.4; ‘diet quality stayed the same’, n=3077: Mean BMI, 26.5±5.2; ‘diet quality improved’, n=2723: Mean BMI, 26.7±5.2 | - [underlined: Did not account for:] N/A; - Dietary change assessed; Selfreported Wt, Ht; BMI data collected at time 1 only; Fruit and Vegetable Index does not meet the definition of a dietary pattern with only 2 groups; - Funding: Australian Department of Health
Baratali, 2021 ^87^; Switzerland; CoLaus\|PsyColaus study; Analytic N=2542; Participant characteristics:; - 38% OW; 14% Ob; mean BMI, baseline: 25.6 ± 4.3; WC, cm, 91; Race and/or Ethnicity: Caucasian, data NR; SEP:; - Education: University: 22%; Secondary: 27%; Apprenticeship: 37%; Primary: 14% | Age at Dietary Pattern: 58.0 +/− 10.4 y at baseline; - Mediterranean Diet Score (MDS) [Trichopolou 2003], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - Mediterranean Diet Score (mMDS) modified [Vormund 2015] mMDS, Positive: Vegetables; Salad; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; - Alternative Healthy Eating Index (AHEI) [McCullough 2000] AHEI, Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans-UFA. Neutral: Alcohol; Factor loadings derived from PCA [Marques-Vidal, 2018]; - ‘Meat & Fries’: Positive: red meat, poultry, processed meat, liver, french fries; - ‘Fruits & Vegetables’: Positive: vegetables, fresh fruit or juice; - ‘Fatty & Sugary’: Positive: hard fats, bakery items, chocolate; Method(s): Factor/Cluster; Index/Score Analysis | Follow-up duration or age:5 y; [underlined: Body weight:]; [underlined: Wt (kg)]; AHEI; Q1, 0.57 ± 0.18; Q2, 0.31 ± 0.17; Q3, 0.32 ± 0.18; Q4, 0.57 ± 0.19; per 1-pt, β: 0.017; p-trend=0.393; MDS; Q1, 0.42 ± 0.15; Q2, 0.59 ± 0.18; Q3, 0.30 ± 0.20; Q4, 0.46 ± 0.22; per 1-pt, β: 0.005; p-trend=0.799; mMDS; Q1, 0.61 ± 0.17; Q2, 0.20 ± 0.15; Q3, 0.61 ± 0.21; Q4, 0.47 ± 0.21; per 1-pt, β: 0.008; p-trend=0.673; ‘Meat & Fries’; Q1, 0.26 ± 0.19; Q2, 0.69 ± 0.18; Q3, 0.45 ± 0.18; Q4, 0.57 ± 0.19; per 1-pt, β: 0.037; p-trend=0.066; ‘Fruits & Vegetables’; Q1, 0.50 ± 0.19; Q2, 0.53 ± 0.18; Q3, 0.20 ± 0.18; Q4, 0.74 ± 0.19; per 1-pt, β: 0.034; p-trend=0.157; ‘Fatty & Sugary’; Q1, 0.81 ± 0.18; Q2, 0.50 ± 0.18; Q3, 0.17 ± 0.18; Q4, 0.49 ± 0.18; per 1-pt, β: −0.026; p-trend=0.198; [underlined: ΔWt (> 5 kg)]; AHEI; Q1, OR: 1, ref; Q2, OR: 0.78, 95% CI: 0.57, 1.08; Q3, OR: 0.71, 95% CI: 0.50, 0.99; Q4, OR: 0.72, 95% CI: 0.51, 1.02; Per 1-pt, OR: 0.99, 95% CI: 0.98, 1.00; p-trend=0.075; MDS; Q1, OR: 1, ref; Q2, OR: 0.86, 95% CI: 0.64, 1.16; Q3, OR: 0.81, 95% CI: 0.58, 1.12; Q4, OR: 0.55, 95% CI: 0.37, 0.82; Per 1-pt, OR: 0.89, 95% CI: 0.82, 0.96; p-trend=0.005; mMDS; Q1, OR: 1, ref; Q2, OR: 0.77, 95% CI: 0.57, 1.03; Q3, OR: 0.94, 95% CI: 0.67, 1.33; Q4, OR: 0.63, 95% CI: 0.43, 0.91; Per 1-pt, OR: 0.94, 95% CI: 0.88, 0.99; p-trend=0.038; ‘Meat & Fries’; Q1, OR: 1, ref; Q2, OR: 1.38, 95% CI: 0.96, 1.98; Q3, OR: 1.09, 95% CI: 0.75, 1.59; Q4, OR: 1.33, 95% CI: 0.91, 1.92; Per 1-pt, OR: 1.12, 95% CI: 1.01, 1.24; p-trend=0.032; ‘Fruit & vegetables’; Q1, OR: 1, ref; Q2, OR: 0.87, 95% CI: 0.62, 1.22; Q3, OR: 0.63, 95% CI: 0.44, 0.91; Q4, OR: 1.00, 95% CI: 0.71, 1.41; Per 1-pt, OR: 1.06, 95% CI: 0.97, 1.15; p-trend=0.189; ‘Fatty & Sugary’; Q1, OR: 1, ref; Q2, OR: 0.73, 95% CI: 0.52, 1.03; Q3, OR: 0.61, 95% CI: 0.43, 0.87; Q4, OR: 0.94, 95% CI: 0.68, 1.29; Per 1-pt, OR: 0.99, 95% CI: 0.91, 1.08; p-trend=0.851; [underlined: BMI:]; AHEI & BMI; Q1, 0.41 ± 0.06; Q2, 0.31 ± 0.06; Q3, 0.31 ± 0.07; Q4, 0.37 ± 0.07; per 1-pt, β: 0.010; p-trend=0.626; MDS & BMI; Q1, 0.35 ± 0.05; Q2, 0.40 ± 0.06; Q3, 0.29 ± 0.07; Q4, 0.34 ± 0.08; per 1-pt, β: −0.001; p-trend=0.942; mMDS & BMI; Q1, 0.40 ± 0.06; Q2, 0.27 ± 0.05; Q3, 0.40 ± 0.08; Q4, 0.35 ± 0.07; per 1-pt, β: 0.003; p-trend=0.899; ‘Meat & Fries’ & BMI; Q1, 0.28 ± 0.07; Q2, 0.43 ± 0.07; Q3, 0.36 ± 0.07; Q4, 0.38 ± 0.07; per 1-pt, β: 0.034; p-trend=0.096; ‘Fruits & Vegetables’ & BMI; Q1, 0.37 ± 0.07; Q2, 0.38 ± 0.06; Q3, 0.26 ± 0.07; Q4, 0.44 ± 0.07; per 1-pt, β: 0.031; p-trend=0.147; ‘Fatty & Sugary’ & BMI; Q1, 0.47 ± 0.07; Q2, 0.36 ± 0.06; Q3, 0.25 ± 0.07; Q4, 0.36 ± 0.07; per 1-pt, β: −0.028; p-trend=0.163; [underlined: Waist/Central:]; AHEI & WC (cm); Q1, 0.96 ± 0.25; Q2, 0.32 ± 0.24; Q3, −0.15 ± 0.25; Q4, 0.11 ± 0.26; per 1-pt, β: −0.041; p-trend= 0.044; MDS & WC (cm); Q1, 0.69 ± 0.20; Q2, 0.13 ± 0.25; Q3, −0.03 ± 0.27; Q4, 0.21 ± 0.31; per 1-pt, β: −0.015; p-trend= 0.438; mMDS & WC (cm); Q1, 0.82 ± 0.23; Q2, 0.28 ± 0.21; Q3, 0.06 ± 0.29; Q4, −0.09 ± 0.28; per 1-pt, β: −0.025; p-trend=0.214; ‘Meat & Fries’ & WC (cm); Q1, −0.09 ± 0.26; Q2, 0.74 ± 0.25; Q3, 0.30 ± 0.25; Q4, 0.45 ± 0.26; per 1-pt, β: 0.019; p-trend=0.342; ‘Fruits & Vegetables’ & WC (cm); Q1, 1.14 ± 0.26; Q2, 0.43 ± 0.25; Q3, −0.13 ± 0.25; Q4, −0.05 ± 0.26; per 1-pt, β: −0.043; p-trend=0.042; ‘Fatty & Sugary’ & WC (cm); Q1, 0.68 ± 0.25; Q2, 0.55 ± 0.25; Q3, −0.01 ± 0.25; Q4, 0.16 ± 0.25; per 1-pt, β: −0.026; p-trend=0.202; AHEI & Hip-C (cm); Q1, 3.45 ± 0.20; Q2, 2.78 ± 0.20; Q3, 2.67 ± 0.21; Q4, 2.96 ± 0.21; per 1-pt, β: −0.005; p-trend=0.803; MDS & Hip-C (cm); Q1, 3.09 ± 0.17; Q2, 2.99 ± 0.21; Q3, 2.49 ± 0.22; Q4, 3.27 ± 0.25; per 1-pt, β: 0.028; p-trend=0.137; mMDS & Hip-C (cm); Q1, 3.06 ± 0.19; Q2, 2.83 ± 0.17; Q3, 3.16 ± 0.24; Q4, 2.9 ± 0.24; per 1-pt, β: 0.038; p-trend=0.049; ‘Meat & Fries’ & Hip-C (cm); Q1, 2.76 ± 0.21; Q2, 3.08 ± 0.21; Q3, 3.27 ± 0.21; Q4, 3.02 ± 0.22; per 1-pt, β: 0.016; p-trend=0.406; ‘Fruits & Vegetables’ & Hip-C (cm); Q1, 3.08 ± 0.22; Q2, 3.32 ± 0.21; Q3, 2.74 ± 0.21; Q4, 2.99 ± 0.21; per 1-pt, β: 0.020; p-trend=0.332; ‘Fatty & Sugary’ & Hip-C (cm); Q1, 3.16 ± 0.21; Q2, 3.17 ± 0.21; Q3, 2.74 ± 0.21; Q4, 3.05 ± 0.21; per 1-pt, β: 0.001; p-trend=0.972; AHEI & ΔWC > 5 cm, Q1, OR: 1, ref; Q2, OR: 0.64, 95% CI: 0.50, 0.82; Q3, OR: 0.60, 95% CI: 0.46, 0.79; Q4, OR: 0.65, 95% CI: 0.50, 0.85; Per 1-pt, OR: 0.98, 95% CI: 0.97, 0.99; p-trend<0.001; MDS & ΔWC > 5 cm, Q1, OR: 1, ref; Q2, OR: 0.75, 95% CI: 0.59, 0.95; Q3, OR: 0.79, 95% CI: 0.61, 1.01; Q4, OR: 0.73, 95% CI: 0.55, 0.97; Per 1-pt, OR: 0.91, 95% CI: 0.86, 0.97; p-trend=0.005; mMDS & ΔWC > 5 cm, Q1, OR: 1, ref; Q2, OR: 0.87, 95% CI: 0.69, 1.10; Q3, OR: 0.81, 95% CI: 0.61, 1.07; Q4, OR: 0.57, 95% CI: 0.43, 0.77; Per 1-pt, OR: 0.92, 95% CI: 0.88, 0.97; p-trend=0.001; ‘Meat & Fries’ & AWC > 5 cm, Q1, OR: 1, ref; Q2, OR: 1.23, 95% CI: 0.94, 1.62; Q3, OR: 1.06, 95% CI: 0.80, 1.39; Q4, OR: 0.98, 95% CI: 0.73, 1.30; Per 1-pt, OR: 1.04, 95% CI: 0.98, 1.09; p-trend=0.201; ‘Fruit & vegetables’ & ΔWC > 5 cm, Q1, OR: 1, ref; Q2, OR: 0.83, 95% CI: 0.64, 1.08; Q3, OR: 0.62, 95% CI: 0.47, 0.82; Q4, OR: 0.67, 95% CI: 0.51, 0.89; Per 1-pt, OR: 0.92, 95% CI: 0.86, 0.99; p-trend=0.019; ‘Fatty & Sugary’ & AWC > 5 cm, Q1, OR: 1, ref; Q2, OR: 0.89, 95% CI: 0.68, 1.15; Q3, OR: 0.75, 95% CI: 0.57, 0.98; Q4, OR: 0.84, 95% CI: 0.64, 1.09; Per 1-pt, OR: 0.95, 95% CI: 0.89, 1.02; p-trend=0.180 | - [underlined: Did not account for:] N/A; - Diet assessed once only for multiple DP scores; No adjustment for multiple testing was conducted; Additional analyses by sex showed similar trends but not significant given a reduced sample size.; - Funding: GlaxoSmithKline, the Faculty of Biology and Medicine of Lausanne, the Swiss National Science Foundation
Beslay, 2020 ^88^; France; NutriNet-Sante; Analytic N=110,260; Wt 71871 Obesity; 55037 Overweight; Participant characteristics: Mean BMI, baseline: 23.8; Race and/or Ethnicity:NR; SEP: Education (baseline): < HS: 18%; <2 y post-HS: 17%; ≥2 y post-HS: 65% | Age at Dietary Pattern: 18 to 73.3 y (mean 43.1 [14.6]) at baseline; [underlined: UPF] (Nova food classification system, group 4 [Monteiro, 2019]) : Fruits and Vegetables (UPF, reconstituted); Starchy foods and breakfast cereals (Industrial or flavored with additives); Meat, fish and egg (Processed/Industrial with additives); Dairy products (flavored or artificially sweetened; with additives); Beverages (sugary drinks, energy drinks, artificially sweetened); Sugary products (industrial cookies, cakes, candies with additives); Fats and sauces (dressing, mayo, ketchup, other with additives); Salty snacks (chips, crisps, crackers with additives e.g., oil, salt, maltodextrin, flavors).; Nova 1, components NR.; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age: 5 y, median; [underlined: Risk of Obesitv/Overweight:]; Overweight (model 3), Q1, HR: 1, ref; Q2, HR: 1.06, 95% CI: 0.99, 1.13; Q3, HR: 1.18, 95% CI: 1.10, 1.26; Q4, HR: 1.24, 95% CI: 1.16, 1.33; p-trend<0.001; per 10%, HR: 1.10, 95% CI: 1.08, 1.13, p<0.001; Obesity (model 3), Q1, HR: 1, ref; Q2, HR: 1.05, 95% CI: 0.95, 1.17; Q3, HR: 1.11, 95% CI: 1.00, 1.23; Q4, HR: 1.16, 95% CI: 1.05, 1.30; p-trend=0.003; per 10%, HR: 1.10, 95% CI: 1.06, 1.14, p<0.001; [underlined: BMI:]; BMI Δ (model 2), Q1, ref; Q2, β 0.01, 95% CI: 0.004 to 0.02; Q3, β 0.01, 95% CI: 0.01 to 0.02; Q4, β 0.04, 95% CI: 0.04 to 0.05; p-trend<0.001; per 10%, β 0.02, 95% CI: 0.01 to 0.02, p<0.001 | [underlined: Did not account for:] Race and/or Ethnicity; - Self-reported weight, height;; - Diet assessed at baseline only with 24 hour-recall; Funding: Ministère de la Santé, Santé Publique France, Institut National de la Santé et de la Recherche Médicale (INSERM), Institut National de la Recherche Agronomique (INRAE), Conservatoire National des Arts et Métiers (CNAM), and Université Sorbonne Paris Nord
Best, 2023 ^89^; United Kingdom; UK Women’s Cohort Study; Analytic N=4162; Participant characteristics:; Race and/or Ethnicity: 99.3% white; SEP: Education (median) differed b/n groups, p<0.001; - MDS T1; ○ No formal: 19.3; ○ O level: 35.7; ○ A level: 25.3; ○ Degree+: 19.6; - MDS T2; ○ No formal: 17.9; ○ O level: 30.5; ○ A level: 27.1; ○ Degree+: 24.5; - MDS T3; ○ No formal: 16.2; ○ O level: 24.9; ○ A level: 29.3; ○ Degree+29.5 | Age at Dietary Pattern: 35 to 69 y at baseline; Mediterranean Diet Score (MDS) [Trichopolou 2003], Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Eat Well Guide (EWG) [Scheelbeek 2020], Positive: Vegetables and Fruit; Fish, oily; Fish, other; Fiber. Negative: Red and Processed Meat; Saturated fat; Sugars, free; Salt, total; Method(s): Index/score analysis | Follow-up duration or age:4.1y, mean; [underlined: Body weight:]; MDS & ΔWt (median, IQR); T1, 0.9, 4.5; T2, 0.3, 1.6; T3, 0.4, 1.6; p-trend=0.20; [underlined: Waist/Central:]; MDS & AWC (median, IQR); T1, 5.7, 8.3; T2, 5.7, 7.6; T3, 5.7, 7.6; p-trend=0.31; linear (per tertile), β: −0.29, 95% CI: −0.58, −0.01; p-trend=0.05; per 1-pt, β: −0.12, 95% CI: −0.23, −0.02; p-trend=0.02; EWG & ΔWC (median, IQR); T1, 6.3, 8.3; T2, 5.7, 7.6; T3, 5.1, 7.6; p-trend=0.01; linear (per tertile), β: −0.47, 95% CI: −0.75, −0.20; p-trend=0.001; per 1-pt, β: −0.24, 95% CI: −0.38, −0.12; p-trend<0.001; In those with WC <88 cm at baseline; MDS & Risk of Abdominal Obesity; T1, OR: 1, ref; T2, OR: 0.74, 95% CI: 0.61, 0.90; T3, OR: 0.60, 95% CI: 0.46, 0.76; Per 1-pt, OR: 0.90, 95% CI: 0.86, 0.94; EWG & Risk of Abdominal Obesity; T1, OR: 1, ref; T2, OR: 0.75, 95% CI: 0.62, 0.90; T3, OR: 0.55, 95% CI: 0.43, 0.70; Per 1-pt, OR: 0.84, 95% CI: 0.80, 0.90 T2, 0.9, 4.1; T3, 0.9, 4.1; p-trend=0.40; linear (per tertile), β: 0.03, 95% CI: −0.19, 0.25; p-trend=0.80; per 1-pt, β: 0.16, 95% CI: −0.06, 0.10; p-trend-0.70; EWG & ΔWt (median, IQR); T1, 0.9, 4.0; T2, 0.9, 4.1; T3, 0.9, 4.5; p-trend=0.20; linear (per tertile), β: 0.14, 95% CI: −0.07, 0.36; p-trend=0.20; per 1-pt, β: 0.06, 95% CI: −0.04, 0.17; p-trend=0.23; [underlined: Risk of Ob/OW], in those with BMI<25 at baseline; MDS; T1, OR: 1, ref; T2, OR: 0.86, 95% CI: 0.65, 1.13; T3, OR: 0.91,95% CI: 0.65, 1.27; Per 1-pt, OR: 0.98, 95% CI: 0.92, 1.04; EWG; T1, OR: 1, ref; T2, OR: 1.19, 95% CI: 0.91, 1.57; T3, OR: 1.09, 95% CI: 0.77, 1.5; [underlined: BMI:]; MDS & ΔBMI (median, IQR); T1, 0.4, 1.7; T2, 0.3, 1.6; T3, 0.3, 1.5; p-trend=0.42; EWG & ΔBMI (median, IQR); T1, 0.3, 1.5 | [underlined: Did not account for:] N/A; - Self-reported anthropometrics; - Diet assessed once only with multiple measures; - Association between MDS and ΔWC (linear, per tertile) approaching significance at p=0.05. No adjustment for multiple analyses; - Analyses examining MDS & EWG categorically (tertiles) did not adjust for any confounders in the models, but there were no differences in age between the tertiles for MDS & EWG, and no differences in education or smoking (p=0.05 for smoking) for EWG. For MDS, tertiles differed in baseline weight, baseline WC, baseline BMI, baseline abdominal obesity, baseline Ov/Ob, physical activity, education, smoking. For EWG, tertiles differed in baseline weight, baseline WC, baseline BMI, baseline abdominal obesity, baseline Ov/Ob, physical activity; Funding: none
Bouzas, 2020 ^91^; Spain; PREDIMED Plus; Analytic N=5695; Participant characteristics:; - Basal BMI: 32–33; between WLM groups, p<0.001; - Max BMI: 33–36; - High-BP, ∼92%; - Hyperglycemia: 72–80%; - HyperTG: 53–58%; - Low HDL: 41–45%; - Abdominal Ob: 95–96%; Race and/or Ethnicity for: NR; SEP: Education by WLM group: Primary: 48–53%; Secondary: 28–29%; Tertiary: 19–23%; | Age at Dietary Pattern: ♀ 60 to 75 y; ♂ 55 to 75 y; modified MedDiet [Alvarez-Alvarez, 2019 (modified Schroder, 2011)]; Healthful/Unhealthful Provegetarian Food Pattern [Gomez-Donoso, 2019]; mMedDiet: Positive: extra virgin olive oil, fruit (including fruit juices), vegetables/garden produce, whole grain cereals and pasta, legumes, fish or shellfish, nuts, chicken, turkey or rabbit, sofritas (dishes made with tomato, onion, leek or garlic), non-caloric artificial sweeteners, wine; Negative: white bread, red meat, hamburgers, or meat products (ham, sausage), butter, margarine, cream, sugary beverages or sugar-sweetened fruit juice, commercial sweets or pastries (not homemade); Provegetarian DP (Proveg.): Positive: Vegetables; Fruits; Legumes; Whole grains; Nuts; Olive oil; Coffee. Negative: Fruit juices; Refined grains; Sugary beverages; Pastries; Dairy; Eggs; Meat; Fish and seafood; Misc. foods, animal fat; Method(s): Index/score analysis | Follow-up duration or age: 1 y; [underlined: Body weight:]; mMedDiet & Δ Wt. mean [SD]; Max: 3.4 [3.3]; Moderate WL Maintainers (WLM): 3.2 [3.4]; Large WLM: 3.1 [3.2]; p=0.046; Healthful Proveg. & Δ Wt, mean [SD]; Max: −0.1 [7.8]; Moderate WLM: −0.1 [7.7]; Large WLM: 0.0 [7.8]; p=NS/NR; Unhealthful Proveg. & Δ Wt, mean [SD]; Maximum −0.7 [8.3]; Moderate WLM: 0.3 [8.5]; Large WLM: 0.2 [8.1]; p=0.013 | - [underlined: Did not account for:] SEP, Race/Ethnicity (100% Spanish), Physical activity, Smoking; - Diet change assessed Δ1y; - Reporting unclear for statistical significance within unhealthful provegetarian DP and WLM; - Increases in MedDiet adherence and healthy provegetarian DP adherence were reported as similar between groups; Funding: European Research Council; Fondo de Investigación para la Salud; Especial Action Project; Recercaixa Grant; Consejería de Salud de la Junta de Andalucía; Generalitat Valenciana; Balearic Islands Government; Balearic Islands Health Research Institte; European Regional Development Fund; the European Commission, Fernando Tarongí Bauzà Grant
Bouzas, 2022 ^90^; Spain; PREDIMED Plus; Analytic N=5499; Participant characteristics:; - All at high risk with BMI 27–40 and/or 3+ criteria for MetSyn.; - Basal BMI, mean: T1: 33; T2: 32; T3: 33, p<0.001; - Max BMI, mean: T1: 34; T2: 33; T3: 35; p<0.001; - High-BP, T1: 93%; T2: 91%; T3: 92%; p=0.053; - Hyperglycemia: T1: 77%; T2: 75%; T3: 75%; p=0.436; - HyperTG: T1: 55%; T2: 57%; T3: 56%, p=0.248; - Low HDL: T1: 44%; T2: 43%; T3: 42%, p=0.295; - Abdominal Ob: T1: 96%; T2: 94%; T3: 98%, p<0.001; Race and/or Ethnicity: NR; SEP:; - Education Level, T3-T1: Primary: 49–52%; Secondary: 27–29%; Tertiary: 21–23% | Age at Dietary Pattern: ♂ 55 to 75 y ♀ 60 to 75 y; modified MEDAS [Alvarez-Alvarez, 2019 (modified Schroder, 2011)] mMEDAS, Positive: Vegetables; Fruit; Legumes; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Wine; Sofritas [pasta/vegetable dishes with Tomato Sauce (tomato, garlic, onion, leek, olive oil)]; Negative: Sweets or Pastries; Red Meat or Sausages; Butter, maragarine; Sugar-Sweetened Beverages; Method(s): Index/score analysis | Follow-up duration or age:1 y; [underlined: Body weight:]; MEDAS & “DWL” (Ideal-measured Wt), mean change (SD), after 1y F/U; DWL >0 kg: Δ2.4 (3.0); DWL-4kg to 0 kg:Δ 3.2 (3.1); DWL <−4kg: Δ 4.2 (3.3); p=0.052 (time*group) | - [underlined: Did not account for:] SEP (NSD in education or marital status), Physical activity (NSD between tertiles; part of outcome); - Diet assessed with validated 143-FFQ at baseline and 1y F/U; Did not directly examine outcome, reported “desired” Wt loss (ideal v. measured); Funding: European Research Council, Fondo de Investigación para la Salud (FIS), co-funded by the European Regional Development Fund, Especial Action Project, Consejería de Salud de la Junta de Andalucía, Generalitat Valenciana, SEMERGEN, Balearic Islands Health Research Institute (IDISBA), European Regional Development Fund, European Commission, Fundació La Marató TV3, Fernando Tarongí Bauzà
Brayner, 2021 ^92^; United Kingdom; BIOBANK; Analytic N=16523 (T2D; CVD; Ob); 14927 (WC); Participant characteristics:; - Excluded those with chronic diseases at baseline; 9.5% w/ family Hx of T2D; Race and/or Ethnicity: 97.5% White; 2% Mixed; 0.5% Other; SEP: Townsend deprivation index: Low, 41%; Medium, 34%; High, 25% | Age at Dietary Pattern: 40 to 69 y at baseline; DP1: Higher intake of nuts, seeds, vegetable dishes, and butter and lower intake of fruit and low-fat yogurt; DP2: Higher intake of butter and high-fat cheese and lower intake of nuts and seeds; Method(s): RRR: Response variables were %E from SFAs, PUFAs, and MUFAs | Follow-up duration or age:6.3 y, mean; [underlined: Risk of Ob/OW:]; DP1 & Ob, T1, ref; T2, OR: 1.13, 95% CI: 0.97, 1.30; T3, OR: 1.06, 95% CI: 0.91, 1.22; p-trend=0.44; DP1, per-unit & Ob: OR: 1.08, 95% CI: 0.98, 1.18; p=0.09; DP2 & Ob, T1, ref; T2, OR: 1.20, 95% CI: 1.04, 1.39; T3, OR: 1.28, 95% CI: 1.11, 1.50; p-trend=0.001; [underlined: BMI:]; DP1 & BMI (cont.): B: 0.00, 95% CI: −0.02, 0.03; p=0.83; DP2, per-unit & BMI (cont.): B: 0.07, 95% CI: 0.05, 0.09; p<0.001; [underlined: Waist/Central:]; DP1 & Abdominal Ob (WC); T1, ref; T2, OR: 0.95, 95% CI: 0.82, 1.09; T3, OR: 0.96, 95% CI: 0.83, 1.11; p-trend=0.66; DP1, per-unit & Abdominal Ob: OR: 1.05, 95% CI: 0.98, 1.12; p=0.19; DP1, per-unit & WC (cont.): OR: 0.08, 95% CI: −0.03, 0.20; p=0.15; DP2 & Abdominal Ob (WC); T1, ref; T2, OR: 1, 95% CI: 0.86, 1.15; T3, OR: 1.22, 95% CI: 1.06, 1.40; p-trend=0.006; DP2, per-unit & Abdominal Ob: OR: 1.07, 95% CI: 1.01, 1.14; p=0.025; DP2, per-unit & WC (cont.): OR: 0.21, 95% CI: 0.12, 0.31; p<0.001 | [underlined: Did not account for:] N/A; - Diet assessed repeatedly with ‘hybrid’ 24h-recall/FFQ; Self-reported DM (did not distinguish T1 v. T2); Funding: NR
Canhada, 2019 ^97^; Brazil; ELSA-Brasil; Analytic N=11827 large wt and waist gains; 4525 incident ovwt/ob; 7056 incident ob among ovwt; Participant characteristics:; - Excluded those with chronic diseases at baseline; Mean BMI, 26.8, WC, cm, 90.6; - 55% Female; Race and/or Ethnicity:; - 16% Black;; - 28.1% Brown;; - 52% White;; - 3% Asian;; - 1% Indigenous; SEP: Median family income, 5x Brazilian minimum wage; - Schooling: 54% college, 35% secondary/HS; Elementary 6%, < Elementary 5% | Age at Dietary Pattern: 35 to 75 y, mean 51 y at baseline; Nova “Ultra-processed” [Monteiro, 2019] Nova 4 sub-groups: Bread; Sweets, candies; Sweetened sodas/juices; Salty pastries, chips; Cakes; Processed meat; Pasta and pizzas; Cookies, crackers; Mayo, margarine, cream cheese; Yogurt with additives; Cereal bars; Distilled alcoholic beverages; Soup; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age:3.8 y, mean; [underlined: Body weight:]; Wt, incident large gain; UPF per-15%, 1.12, 95% CI: 1.03,1.22; Q1, ref; Q2, RR: 1.15, 95% CI: 0.97,1.37; Q3, RR: 1.2, 95% CI: 1.02,1.42; Q4, RR: 1.27, 95% CI: 1.07,1.5; *Stronger association in non-Whites than other skin colour groups; [underlined: Risk of Ob/OW:]; OW/Ob, n=4527, Q1, ref; Q2, RR: 1.14, 95% CI: 0.98,1.33; Q3, RR: 1.36, 95% CI: 1.18,1.57; Q4, RR: 1.2, 95% CI: 1.03,1.4; Ob, n=4771, Q1, ref; Q2, RR: 1.12, 95% CI: 0.95,1.32; Q3, RR: 1.01, 95% CI: 0.85,1.21; Q4, RR: 1.02, 95% CI: 0.85,1.21; per-15%, 1.06, 95% CI: 0.96,1.17; [underlined: Waist/Central:]; WC, incident large gain, Q1, ref; Q2, RR: 1.11, 95% CI: 0.94,1.33; Q3, RR: 1.23, 95% CI: 1.04,1.46; Q4, RR: 1.33, 95% CI: 1.12,1.58; per-15%, 1.15, 95% CI: 1.06,1.25 | [underlined: Did not account for:] TEI; - Diet assessed once at baseline only with validated FFQ, but FFQ was not designed for UPF via Nova classification; additional analyses: adjusted further for TEI, F/V intake, excluding sweetened beverages; and tested interactions between sex, race/color, and age; Funding: Brazilian Ministry of Health (Department of Science and Technology) and Ministry of Science, Technology and Innovation; National Council for Scientific and Technological Development
Canhada, 2022 ^96^; Brazil; ELSA-Brasil; Analytic N= 8065; Participant characteristics:; - 62% never smoked; Race and/or Ethnicity: 14% Black, 27% Brown, 55% White, 3% Asian, 1% Indigenous; SEP: Education: 59% college degree; Income: 747–2352 Brazilian reais (P25-P75) | Age at Dietary Pattern: 49 y, mean at baseline; Nova “Ultra-processed” [Monteiro, 2019], Nova 4 e.g., packaged products such as bread (light, toasted, sweet, whole grain), cheese bread, simple cake, stuffed cake, salty biscuit, sweet biscuit with filling, sweet biscuit without filling, light mayonnaise, mayonnaise, light sweetened yogurt, sweetened yogurt, light cream cheese, cream cheese, margarine/vegetable cream, sausage, hamburger (steak), sliced turkey breast, ham/mortadella/ salami, ready-packaged pizza, instant noodles, baked snacks, fried snacks, afro-Brazilian bean fritter (acaraje), hot dogs, instant soup, creamy ice cream, fruit popsicle, caramel/candy, gelatin, chocolate powder, chocolate bar, pudding, fruit jam/jelly, cereal bar, diet soda, soda, industrialized juice with sugar, industrialized juice without sugar, industrialized juice with sweetener, artificial juice with sugar, artificial juice without sugar, artificial juice with sweetener, distilled alcoholic beverages.; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age: ∼8 y; [underlined: Waist/Central:]; Nova 4 700 v. 234 g/d (ref) & WC +0.7cm, p=0.003 | [underlined: Did not account for:] TEI; - Diet assessed once via FFQ; - Misclassification to Nova 4 from FFQ likely; - Outcomes objectively measured; - Indirect outcome of MetS; Funding: Brazilian Ministry of Health (Department of Science and Technology) and Ministry of Science, Technology and Innovation; National Council for Scientific and Technological Development
Cespedes Feliciano, 2016 ^99^; United States; WHI; Analytic N=67175; Participant characteristics:; - 100% female; - By diet index, Q4 – Q1:; - Mean BMI, ∼ 26–29;; - Wt kg ∼ 67–75;; - WC cm ∼81–89;; - Family Hx DM ∼ 29%–33%; Race and/or Ethnicity: ∼ by diet index: ∼78–91% White; 4–12% Black; 2–4% Asian; 2–5% Latino; 1–2% Other; SEP:; - 10–14% ≥ College education; | Age at Dietary Pattern: 50 to 79 y, mean 63 y, at baseline; Alternative HEI (AHEI)-2010 [Chiuve 2012] Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; DASH Score [Fung 2008], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Healthy Eating Index (HEI-2010) [Guenther 2013], Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; Alternate Med Diet Score (aMED) [Fung 2005];aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:3 y; [underlined: Adiposity:]; ΔAHEI-2010 & Δ trunk fat; <10% Δ: 0, ref; 10% increase: −195, 95% CI: −327, −62; 10% decrease: −14, 95% CI: −163, 135; per 10%: −73, 95% CI:−126, −21; Δ DASH & Δ trunk fat; <10% Δ: 0, Ref; 10% increase: −130, 95% CI: −249, −10; 10% decrease: 77, 95% CI: −42, 195; per 10%: −45, 95% CI: −83, −7; Δ HEI-2010 & Δ trunk fat; <10% Δ: 0, Ref; 10% increase: −66, 95% CI: −190, 58; 10% decrease: 93, 95% CI: −48, 233; per 10%: −63, 95% CI: −111, −15; Δ aMED & Δtrunk fat; <10% Δ: 0, Ref; 10% increase: 3, 95% CI: −108, 114; 10% decrease: 43, 95% CI: −66, 152; per 10%: −7, 95% CI: −32, 18; [underlined: Waist/Central:] Mean differences; AHEI-2010 & Δ WC; Q4: 0, Ref; Q3: 0.11, 95% CI: −0.01, 0.24; Q2: 0.29, 95% CI: 0.17, 0.42; Q1: 0.45, 95% CI: 0.32, 0.58; Per 10%: −0.20, 95% CI: −0.24, −0.15; DASH & Δ WC; Q4: 0, Ref; Q3: 0.10, 95% CI: −0.03, 0.23; Q2: 0.26, 95% CI: 0.14, 0.38; Q1: 0.48, 95% CI: 0.34, 0.62; Per 10%: −0.14, 95% CI: −0.18, −0.11; HEI-2010 & Δ WC; Q4: 0, Ref; Q3: 0.15, 95% CI: 0.02, 0.27; Q2: 0.27, 95% CI: 0.15, 0.40; Q1: 0.48, 95% CI: 0.34, 0.61; per 10%: −0.18, 95% CI: −0.22, −0.13; aMED & Δ WC; Q4: 0, Ref; Q3: 0.20, 95% CI: 0.07, 0.34; Q2: 0.33, 95% CI: 0.21, 0.44; Q1: 0.48, 95% CI: 0.34, 0.62; per 10%: −0.10, 95% CI: −0.12, −0.07; ΔAHEI-2010 & Δ WC; <10% Δ: 0, Ref; 10% increase: −0.02, 95% CI: −0.15, 0.12; 10% decrease: 0.31, 95% CI: 0.16, 0.47; Per 10% increase: −0.10, 95% CI: −0.15, −0.04; Δ DASH & Δ WC; <10% Δ: 0, Ref; 10% increase: 0.01, 95% CI: −0.11, 0.13; 10% decrease: 0.28, 95% CI: 0.16, 0.41; Per 10% increase: −0.07, 95% CI: −0.11, −0.03; Δ HEI-2010 & Δ WC; <10% Δ: 0, Ref; 10% increase: 0.02, 95% CI: −0.11, 0.15; 10% decrease: 0.37, 95% CI: 0.22, 0.52; Per 10% increase: −0.11, 95% CI: −0.16, −0.06; Δ aMED & Δ WC; <10% Δ: 0, Ref; 10% increase: −0.06, 95% CI: −0.17, 0.05; 10% decrease: 0.01, 95% CI: −0.10, 0.12; Per 10% increase: −0.02, 95% CI: −0.04, 0.01 | [underlined: Did not account for:] N/A; - Dietary change assessed; - Results stratified by age suggested younger (<65 y) differed than older (>65y) participants; Funding: NHLBI
Chamel, 2019 ^100^; France; NutriNet-Sante; Analytic N=54089 (All); 44026 (Ob); 32954 (OW); Participant characteristics:; - 100% Ob/OW at baseline; Mean BMI, 23.9; Race and/or Ethnicity: NR; SEP:; - Income: ≤1800/CU, 43%; 1800–2700/CU, 27%; >270; - Occupation: Farmer/self-employed, 2%; Managerial, 23%; Employee, 16%; Student, 6%; Manual worker, 1%; Intermediate, 17%; Retired, 24%; Unemployed, 11%; - Education: Primary, 1%; Secondary, 36%; University, 64% | Age at Dietary Pattern: 47y (14.1); ≥ 18 y at baseline; Programme National Nutrition Sante Guideline Score, updated for 2017 Guidelines - France (PNNS-GS2) [modified Estaquio 2009 by Chaltiel 2019]: Positive: Fruits & vegetables (preferably organic); nuts; legumes (preferably organic); whole grain foods (preferably organic); milk and dairy products. Neutral: breads, cereals, potatoes; meat, poultry, seafood, and eggs Negative: Red meat; processed meat (prefer white ham over other processed meat); fish and seafood; added fat (preferably vegetable fat over animal fat); sugary foods; sweet-tasting beverages; alcohol beverages; salt; Method(s): Index/score analysis | Follow-up duration or age:6.0 y, median; [underlined: Risk of Ob/OW:]; PNNS-GS2 & Risk of OW, Q1, HR: 1, ref; Q2, HR: 0.80, 95% CI: 0.72, 0.87; p-trend<0.001; Q3, HR: 0.75, 95% CI: 0.68, 0.82; p-trend<0.001; Q4, HR: 0.59, 95% CI: 0.54, 0.66; p-trend<0.001; Q5, HR: 0.48, 95% CI: 0.43, 0.54; p-trend<0.001; Per 1-pt, 0.92, 95% CI: 0.91, 0.93;; [underlined: BMI:]; PNNS-GS2 & ΔBMIlog; per SD, β: −0.00075, 95% CI: −0.00090, −0.00060; p-trend<0.001 | [underlined: Did not account for:] N/A; - Self-reported Wt, Ht but validated against clinically measured (94%–99% ICC); - PNNS-G1 is multi-component with PA so data were excluded; - Components of sPNNS-G2 were NR so data were excluded; Funding: French Ministry of Health; French Public Health Agency; French National Institute for Health and Medical Research; French National Institute for Agricultural Research; National Conservatory for Arts and Crafts; Paris 13 University
Chen, 2019 ^101^; Netherlands; Rotterdam Study; Analytic N=9633; Participant characteristics:; - Mean BMI, 26.8; WC, cm, 91.6; FMI, 9.2; BF%, 34.2%; Race and/or Ethnicity: NR; SEP:; - Education: Higher, 15%; Intermediate, 28%; Lower, 41%; Primary, 16% | Age at Dietary Pattern: ≥45 y at baseline; modified plant-based diet index (mPDI) [Chen, 2019 via Satija, 2016; Martinez-Gonzalez 2014], Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Alcoholic beverages (wine, beer, liquor, eggnog); Negative: Low-fat milk; Low-fat yogurt; Full-fat milk; Full-fat yogurt; Cheese; Desserts-Sugary dairy; Unprocessed lean meat; Fish; Eggs; Animal fats; Processed and red meat (beef, pork, meatballs, sate, bacon, liver, processed meats); Method(s): Index/score analysis | Follow-up duration or age:7.1 y, median; range 0–25 y; [underlined: Adiposity:]; FMI, Q1, ref; Q2, β: −0.59, 95% CI:−0.89, −0.29; Q3, β: −0.83, 95% CI:−1.1, −0.52; Q4, β: −1.0, 95% CI:−1.3, −0.76; Q5, β: −1.5, 95% CI:−1.8, −1.2; p<0.001; BF %, Q1, ref; Q2, β: −0.94, 95% CI:−1.6, −0.28; Q3, β: −1.7, 95% CI:−2.3, −0.98; Q4, β: −2.0, 95% CI:−2.6, −1.3; Q5, β: −2.9, 95% CI:−3.6, −0.25; p<0.001; [underlined: BMI:]; BMI, Q1, ref; Q2, β: −0.51, 95% CI:−0.77, −0.26; Q3, β: −0.57, 95% CI:−0.84, −0.30; Q4, β: −0.81, 95% CI:−1.1, −0.55; Q5, β: −1.3, 95% CI:−1.6, −0.99; p<0.001; [underlined: Waist/Central:]; WC, Q1, ref; Q2, β: −1.5, 95% CI:−2.1, −0.83; Q3, β: −2.0, 95% CI:−2.7, −1.3; Q4, β: −2.7, 95% CI:−3.4, −2.1; Q5, β: −4.1, 95% CI:−4.8, −3.3; p<0.001 | - [underlined: Did not account for:] Race and/or Ethnicity, Anthropometry; - Diet assessed at baseline only with validated FFQ; - Results were similar with adjustment for baseline health conditions or exclusion of those with Ob/DM/CHD/Cz; exclusion of alcohol; adjustment of baseline diet quality or physical activity; exclusion of less-healthy-plant foods; - Moderate attenuation was found with exclusion of healthy-plant foods or eggs/fish/low-fat yogurt; Funding: Erasmus University Medical Center^*^; * Additional funders for Choi, 2020: Erasmus University Rotterdam; Netherlands Organization for Health Research and Development; Research Institute for Diseases in the Elderly; Netherlands Genomics Initiative; Ministry of Education, Culture and Science; Ministry of Health, Welfare and Sports; European Commission; Municipality of Rotterdam
Choi, 2020 ^102^; United States; Coronary Artery Risk Development in Young Adults (CARDIA); Analytic N=2436 for BMI; 2434 for WC; 2439 for Wt; 2534 for T2D; Participant characteristics:; - Baseline BMI: <median APDQS: Q1,25.2; Q3, 24.6; Q5, 23.9; >median APDQS: Q1, 23.9; Q3, 23.3; Q5, 23.1; - Baseline WC, cm: <median APDQS: Q1,80.1; Q3, 77.8; Q5, 76.0; >median APDQS, Q1, 76.1; Q3, 75.5; Q5, 74.5; - Parental Hx DM: <median APDQS Q1, 28.6%; Q3, 31.8%; Q5, 28.1%; > median APDQS Q1, 22.6%; Q3, 18.4%; Q5, 25.0%; Race and/or Ethnicity: %White, by quantile of 20-y change,; - <median Y0 APDQS: Q1, 34.9%; Q3, 31.8%; Q5, 37.4%; - >median Y0 APDQS: Q1, 72.2%; Q3, 83.7%; Q5, 83.0%; SEP: Highest Education, years; by quantile of 20-y change; - < median APDQS: Q1, 14.7; Q3, 15.0; Q5, 15.7; - > median APDQS: Q1, 16.5; Q3, 16.8; Q5, 17.0 | Age at Dietary Pattern: 18 to 30 y at baseline; a priori diet quality score, APDQS [Sjitmsa, 2012], Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish; Lean fish; Poultry; Low-Fat Dairy; Vegetable Oil; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; Processed meats; Organ meats; Fried Fish/Poultry; High-Fat Dairy; Pastries; Sweets; Desserts; Sugar-sweetened soft drinks; Butter; Fried Foods; Salty Snacks; Sauces. Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Lean meat; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Sugar substitutes; Diet drinks; Method(s): Index/score analysis | Follow-up duration or age:30 y; [underlined: Body weight:]; APDQS (Y0) & ΔWt (Y0-Y20): β= −1.65 (0.36); p<0.001; APDQS (Y0) & ΔWt (Y20-Y30): β= −0.61 (0.25); p=0.014; APDQS (Y0) & ΔWt (Y0-Y7): β= −0.91 (0.22); p<0.001; APDQS (Y0) & ΔWt (Y7-Y30): β= −1.34 (0.36); p<0.001; APDQS (Y7) & ΔWt (Y7-Y30): β= −0.92 (0.32); p=0.004; APDQS (Y20) & ΔWt (Y20-Y30): β= −0.20 (0.21); p=0.32; ΔAPDQS (Y0-Y7) & ΔWt (Y0-Y7): β= −0.71 (0.22); p=0.001; ΔAPDQS (Y0-Y7) & ΔWt (Y7-Y30): β= −0.53 (0.36); p=0.14; ΔAPDQS (Y0-Y20) & ΔWt (Y0-Y20): β= −1.14 (0.33); p<0.001; ΔAPDQS (Y0-Y20) & ΔWt (Y20-Y30): β= −0.05 (0.23); p=0.84; [underlined: BMI:]; APDQS (Y0) & ΔBMI (Y0-Y20): β= −0.65 (0.14); p<0.001; APDQS (Y0) & ΔBMI (Y20-Y30): β= −0.37 (0.11); p<0.001; APDQS (Y0) & ΔBMI (Y0-Y7): β= −0.36 (0.08); p<0.001; APDQS (Y0) & ΔBMI (Y7-Y30): β= −0.53 (0.13); p<0.001; APDQS (Y7) & ΔBMI (Y7-Y30): β= −0.36 (0.11); p=0.001; APDQS (Y20) & ΔBMI (Y20-Y30): β= −0.24 (0.09); p=0.008; ΔAPDQS (Y0-Y7) & ΔBMI (Y0-Y7): β= −0.26 (0.08); p<0.001; ΔAPDQS (Y0-Y7) & ΔBMI (Y7-Y30): β= −0.22 (0.13); p=0.08; ΔAPDQS (Y0-Y20) & ΔBMI (Y0-Y20): β= −0.39 (0.14); p=0.004; ΔAPDQS (Y0-Y20) & ΔBMI (Y20-Y30): β= −0.17 (0.10); p=0.09; [underlined: Waist/Central:]; APDQ (Y0) & ΔWC (Y0-Y20): β= −1.35 (0.29); p<0.001; APDQS (Y0) & ΔWC (Y20-Y30): β= −0.77 (0.22); p<0.001; APDQS (Y0) & ΔWC (Y0-Y7): β= −1.14 (0.20); p<0.001; APDQS (Y0) & Δ WC (Y7-Y30): β= −0.92 (0.30); p=0.002; APDQS (Y7) & Δ WC (Y7-Y30): β= −0.47 (0.27); p=0.08; APDQS (Y20) & ΔWC (Y20-Y30): β= −0.31 (0.19); p=0.10; ΔAPDQS (Y0-Y7) & ΔWC (Y0-Y7): β= −0.80 (0.20); p<0.001; ΔAPDQS (Y0-Y7) & Δ WC (Y7-Y30): β= −0.09 (0.31); p=0.78; ΔAPDQS (Y0-Y20) & ΔWC (Y0-Y20): β= −0.90 (0.27); p<0.001; ΔAPDQS (Y0-Y20) & ΔWC (Y20-Y30): β= −0.10 (0.21); p=0.64 | - [underlined: Did not account for:] N/A; - Diet change assessed ΔY0–7; Y7–30; Y20-Y30; APDQS components NR clearly based on references cited; Funding: NHLBI; University of Minnesota Twin Cities
Cordova, 2021 ^103^; Denmark, France, Germany, Greece, Italy, the Netherlands, Norway, Spain, Sweden, and the United Kingdom; EPIC Analytic N=348748; Participant characteristics:; - OW: 31–38%; Ob:10–14%; BMI <25 48–59%; - Previous illness, T2D, CVD, cancer: 7–8%; Race and/or Ethnicity: NR; SEP: University degree: Q1, 23%; Q2, 24%; Q3, 26%; Q4, 37%; Q5, 25% | Age at Dietary Pattern: 25 to 70 y at baseline; Nova “Ultra-processed” [Monteiro, 2019]; Nova 4, UPF Q5 v. Q1: Similar rmMED scores betwen quantiles; Higher in (not statistically tested): Dairy; Sugar/confectionary; Cakes/biscuits; Soft drinks; Lower in: Fruit; Legumes; Meat/meat products; Fish; Cereals; Alcoholic drinks; Similar Vegetables; Egg; Potatoes; Added Fat; Coffee; Nova 4 w/o alcoholic drinks: e.g., Vegetables and legumes in ultra-processed medium; Potato products; Breads (UPF); Pastries, buns, and cakes; Biscuits; Breakfast cereals; Pizza and focaccia (dough); Pasta (filled); Processed meat (beef, pork and fish); Meat alternatives; Dairy substitute products; Processed cheese; Dairy desserts and drinks (UPF version); Ice cream, ice pops and frozen yogurts; Industrial desserts; Fruit drinks, iced tea and other sweetened beverages; Beverages dry weight; Artificial sweeteners; Sweet snacks; Soft drinks; Packaged salty snacks; Instant and canned soups; ; Margarine; Vegetable spread and products; Alcohol-free versions of alcoholic beverages; Other: Ready meals; Nutrition powders and drinks; Sauces, dressing and gravies; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age:5 y, median; [underlined: Body weight:]; Weight gain; per SD/d, β: 0.118, 95% CI: 0.085, 0.151; Q1, β: 1, ref; Q2, β: −0.009, 95% CI: −0.095, 0.076; Q3, β: 0.101, 95% CI: −0.002, 0.205; Q4, β: 0.193, 95% CI: 0.105, 0.282; Q5, β: 0.352, 95% CI: 0.262, 0.442; p-trend<0.001 | - [underlined: Did not account for:] Race and/or Ethnicity; - Diet assessed at baseline with different validated FFQs for 3rd cohort wave; Outcomes at baseline were measured in some countries and self-reported in others; Residual method was used for energy adjustment; - Conducted repeat analyses substituting Nova 1 for Nova 4; Conducted a range of sensitivity tests (Soft drinks as driver; by Sex, by Age, by BMI); Funding: Fondation de France; National cohorts supported by individual funders^*^; * Additional funders of Cordova, 2021: Ligue Contre le Cancer, Institut Gustave-Roussy, Mutuelle Générale de l'Education Nationale, Institut National de la Santé et de la Recherche Médicale (France); German Cancer Aid, German Cancer Research Center Federal Ministry of Education and Research (Germany); Associazione Italiana per la Ricerca sul Cancro-AIRC-Italy and National Research Council (Italy); Dutch Ministry of Public Health,Welfare and Sports, Netherlands Cancer Registry (NKR), LK Research Funds, Dutch Prevention Funds, Dutch ZON (Zorg Onderzoek Nederland),World Cancer Research Fund, Statistics Netherlands (The Netherlands); Health Research Fund (FIS-ISCIII), the Regional Governments of Andalucía, Asturias, Basque Country, Murcia, Navarra, and the Catalan Institute of Oncology (Barceloan), Spain); Cancer Research UK and Medical Research Council (EPIC-Norfolk; EPIC-Oxford))
Cuenca-Garcia, 2014 ^105^; United States; Aerobics Center Longitudinal Study (ACLS); Analytic N=12449; Participant characteristics:; - Mean BMI, baseline, 25.8; - DM, 3.1%; HTN, 27.5%; Abnormal ECG, 8.1%; Hypercholesterolemia, 30.5%; Parental Hx CVD, 26.9%; - Mean TC, mg/dL, 207.5; - Mean FBG, mg/dL, 99.2; - Mean SBP, mm Hg, 120; - Mean DBP, mm Hg, 80; Race and/or Ethnicity: >95% non-Hispanic white; SEP: predominantly “well educated, middle to upper socioeconomic strata” | Age at Dietary Pattern: 20 to 84 y, at baseline; Ideal Diet Index (IDI) [Cuenca-Garcia, 2014]; Diet Quality Index (DQI) [Patterson, 1994]; Mediterranean Diet Score (MDS) [Trichopolou, 2003]; IDI, Positive: Vegetables and Fruit; Legumes, Nuts, and Seeds; Whole Grains; Fish. Negative: Processed Meat; Added Sugar; SFA; Sodium; DQI, Positive: Vegetables and Fruit; Breads, Cereal, and Legumes; Calcium. Negative: Total Fat; SFA; Cholesterol; Protein; Sodium; MDS, Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; - Method(s): Index/score analysis | Follow-up duration or age:11.6 y, mean; [underlined: BMI:]; IDI, mean diff (SE); Q1, 26.3 (0.06); Q2, 25.9 (0.06); Q3, 25.5 (0.07); Q4, 24.9 (0.09), p<0.001; MDS, mean diff (SE); Q1, 26.5 (0.07); Q2, 26.1 (0.07); Q3, 25.6 (0.05); Q4, 25 (0.08), p<0.001; DQI, mean diff (SE); Q1, 26.9 (0.07); Q2, 26.2 (0.07); Q3, 25.5 (0.06); Q4, 24.8 (0.07), p<0.001 | - [underlined: Did not account for:] Anthropometry; SEP (all higher SES but NR); - Diet assessed once from 3-d records; Funding: NIH; Coca-Cola; Spanish Grants from the Ministry of Economy and Competitiveness
Ericson, 2019 ^107^; Sweden; Malmo; Analytic N=2627, Wt; 20487, CVD; 20487, T2D; Participant characteristics:; - Excluded those with DM, CVD; - mean BMI, baseline:; - ♀ Q1, 25.2; Q2, 25; Q3, 25.2; Q4, 25.1; Q5, 25; p=0.01; - ♂ Q1, 26.0; Q2, 26.1; Q3, 26.0; Q4, 26.1; Q5, 26.2;p=0.09; Race and/or Ethnicity: NR; SEP:; - High education (>10 yrs), by ‘health conscious’ quantiles; - ♀ Q1, 21.5; Q2, 27.0; Q3, 29.7; Q4, 34.1; Q5, 38.4, p<0.001; - ♂ Q1, 27.1; Q2, 29.2; Q3, 33.5; Q4, 38.1; Q5, 44.3, p<0.001 | Age at Dietary Pattern: 45 to 74 y at baseline; ‘Health-Conscious’: Higher loadings for cottage cheese (women) or cream (men), fibre-rich bread, fruits, vegetables, breakfast cereals, fish and low-fat yoghurt; lower loadings for low-fibre bread, red and processed meat, sugar-sweetened beverages; ‘Low-Fat Products’: Higher loadings for low-fat margarines, low-fat milk, low-fat yoghurt; lower loadings for butter; ‘Dressing-Vegetables’: Higher loadings for dressing/oils, vegetables, poultry, salty snacks, rice/pasta, fried potatoes, cheese; lower loadings for boiled potatoes, jam/sugar; Method(s): Factor/Cluster | Follow-up duration or age:16.7 y, mean; [underlined: Body weight:]; ‘Health conscious’ ♀ & Wt Δ; Q1, β: 1.93 ± 1.26; Q2, β: 2.10 ± 1.27; Q3, β: 2.30 ± 1.25; Q4, β: 1.96 ± 1.26; Q5, ref1.97 ± 1.25; p-trend, quintiles= 0.81; p-trend, cont.=0.89; ‘Low-fat products’ ♀ & Wt Δ; Q1, β: 1.77 ± 1.25; Q2, β: 2.45 ± 1.25; Q3, β: 2.07 ± 1.26; Q4, β: 2.12 ± 1.26; Q5, ref2.15 ± 1.25; p-trend, quintiles= 0.68; p-trend, cont.=0.91; ‘Dressing and vegetables’ ♀ & Wt Δ; Q1, β: 1.96 ± 1.25; Q2, β: 1.84 ± 1.26; Q3, β: 1.81 ± 1.25; Q4, β: 1.90 ± 1.26; Q5, ref2.46 ± 1.25; p-trend, quintiles= 0.20; p-trend, cont.=0.16; ‘Health conscious’ ♂ & Wt Δ; Q1, β: 2.04 ± 1.17; Q2, β: 1.65 ± 1.17; Q3, β: 1.12 ± 1.17; Q4, β: 1.40 ± 1.16; Q5, ref1.11 ± 1.15; p-trend, quintiles= 0.03; p-trend, cont.=0.09; ‘Low-fat products’ ♂ & Wt Δ; Q1, β: 1.11 ± 1.18; Q2, β: 1.44 ± 1.16; Q3, β: 1.42 ± 1.16; Q4, β: 1.14 ± 1.17; Q5, ref1.14 ± 1.17; p-trend, quintiles= 0.76; p-trend, cont.=0.78; ‘Dressing and vegetables’ ♂ & Wt Δ; Q1, β: 1.31 ± 1.18; Q2, β: 1.56 ± 1.17; Q3, β: 1.28 ± 1.16; Q4, β: 1.08 ± 1.16; Q5, ref1.15 ± 1.16; p-trend, quintiles= 0.99; p-trend, cont.=0.93 | - [underlined: Did not account for:] Race/Ethnicity (all living in Sweden; speaking Swedish); - Diet assessed once at baseline using validated diet history methods; Funding: Swedish Research Council, the Region Skåne, the Skåne University Hospital, the Novo Nordic Foundation, the Albert Påhlsson Research Foundation
Ford, 2017 ^109^; United States; WHI; Analytic N=88805; Participant characteristics:; - OW 34.1%; Ob class I, 15.3%; Ob class II, 5.5%; Ob class III, 3.4%; - WC, cm <88, 66.3%; ≥88, 33.7%; Race and/or Ethnicity: 84% Non-Hispanic White; 8% Non-Hispanic Black; 4% Hispanic; 3% Other; SEP:; - Education completed: < HS, 21.0%; HS, 36.2%; Some college, 11.5%; BS+, 30.5%; - HH Income (annual): <$20K, 14.4%; $20K-$49.9K, 40.2%; $50K-$99.9K, 27.8%; ≥$100K, 10.3% | Age at Dietary Pattern: 49 to 81 y, mean 63.6 y, at baseline; Low-fat diet: Fruit, 3 serv; Vegetables, 3 serv; Total grains, 5 oz.eq. (1-whole grains; 2–3-non-whole grains); Reduced-carbohydrate diet: Fruit, 1 serv; Vegetables, 1–2 serv.; Total grains, 5 oz.eq. (1-whole grains; 3–4 non-whole grains); Healthy Eating Index (HEI-2010) [Guenther 2013], Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium (data also reported moderate alcohol); Alternate Med Diet Score (aMED) [Fung 2005], Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age: 6.9 y, mean; [underlined: Body weight:]; Low-fat diet & ≥ 10% Wt gain; Q1 (high adherence): OR: 1.43, 95% CI: 1.33, 1.54; Q2: OR: 1.14, 95% CI: 1.06, 1.22; Q3: OR: 1.05, 95% CI: 0.97, 1.13; Q4: OR: 0.99, 95% CI: 0.93, 1.07; Q5 (low adherence): OR: 1, ref; P-trend < 0.001; Reduced-carbohydrate diet & ≥ 10% Wt gain; Q1 (high adherence): OR:0.71, 95%CI: 0.66, 0.76; Q2: OR: 0.71, 95% CI: 0.67, 0.76; Q3: OR: 0.77, 95% CI: 0.73, 0.82; Q4: OR: 0.84, 95% CI: 0.80, 0.88; Q5 (low adherence): OR: 1, ref; P-trend < 0.001; High aMED (Q5) “Mediterranean-style” & ≥ 10% Wt gain; Q1 (low adherence): OR: 1, ref; Q2: OR: 0.99, 95% CI: 0.94, 1.05; Q3: OR: 1.01, 95% CI: 0.96, 1.07; Q4: OR: 1.00, 95% CI: 0.94, 1.07; Q5 (low adherence): OR: 0.95, 95% CI: 0.88, 1.03; P-trend = 0.513; High HEI-2010 (Q5) “DGA diet” & ≥ 10%; Wt gain; Q1 (low adherence): OR: 1, ref; Q2: OR: 1.04, 95% CI: 0.97, 1.11; Q3: OR: 1.07, 95% CI: 1.00, 1.14; Q4: OR: 1.14, 95% CI: 1.07, 1.22; Q5 (low adherence): OR: 1.24, 95% CI: 1.15, 1.33; P-trend < 0.001 | - [underlined: Did not account for:] Alcohol (HEI-2010); - Diet assessed once at baseline only with FFQ for multiple DPs; - Foods consumed not clearly reported for Low-fat and “Reduced-carbohydrate” diets; Funding: NIH, NHLBI, USDHHS
Fung, 2015 ^111^; United States; NHS I, NHS II, HPFS; Analytic N=50603 from NHS; 22973 from HPFS; 72495 from NHS II; Participant characteristics:; - Mean BMI, baseline:NHS, 23.7; HPFS, 24.7; NHS II, 23.0; - Baseline OW%: NHS, 31.0%; HPFS, 46.5%; NHS II, 23.8%; Race and/or Ethnicity: NR; SEP: NR employed in medical-field | Age at Dietary Pattern: 49 y (mean, NHS I), 36 y (mean, NHS II); 48 y (mean, HPFS) at baseline; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Alternate Med Diet Score (aMED) [Fung 2009; Fung 2005]; DASH Score [Fung 2008]; AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; aMED: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; DASH: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method(s): Index/score analysis | Follow-up duration or age:20 y total, NR; [underlined: Body weight:]; Wt Δ, kg, per SD increase in DP; AHEI-2010, pooled NHS, HPFS, NHS-II: −0.47, 95% CI: −0.67, −0.26; aMed, pooled NHS, HPFS, NHS-II: −0.23, 95% CI: −0.30, −0.16; DASH, pooled NHS, HPFS, NHS-II: −0.42, 95% CI: −0.54, −0.29; Mean difference in Wt Δ, kg, pooled NHS, HPFS, NHS-II; AHEI-2010, pooled NHS, HPFS, NHS-II; Q3: 0, ref; Q1: 0.56, 95% CI: 0.39, 0.74; Q2: 0.06, 95% CI: −0.08, 0.20; Q4: −0.12, 95% CI: −0.25, −0.01; Q5: −0.69, 95% CI: −1.06, −0.32; aMed, pooled NHS, HPFS, NHS-II; Q3: 0, ref; Q1: 0.33, 95% CI: 0.19, 0.48; Q2: 0.13, 95% CI: −0.09, 0.17; Q4: −0.10, 95% CI: −0.17, −0.03; Q5: −0.35, 95% CI: −0.48, −0.21; DASH, pooled; Q3: 0, ref; Q1: 0.52, 95% CI: 0.37, 0.68; Q2: 0.15, 95% CI: 0.11, 0.19; Q4: −0.14, 95% CI: −0.23, −0.04; Q5: −0.55, 95% CI: −0.73, −0.38 | - [underlined: Did not account for:] Race/ethnicity, SEP (employed in medical-field), Total E; - Self-reported Wt, Ht but validated;; - Diet change assessed Δ4y; Results reported by each cohort (ie by sex); stratified by BMI (similar results of higher diet quality scores & less weight gain); by age (<55y compared to those ≥ 55y–65y had less weight gain for each SD increase in diet quality); Funding: NIH
Fung, 2021 ^110^; United States; NHS II; Analytic N=68336; Participant characteristics: 100% Female; Race and/or Ethnicity: NR; SEP: NR (health professionals) | Age at Dietary Pattern: 25 to 42 y at baseline; Global Diet Quality Score (GDQS; modified Prime DQ score) [Fung, 2018]; GDQS: Positive: Vegetables (dark green leafy); Vegetables (Cruciferous); Vegetables (Deep Orange); Vegetables (Other); Tubers (Deep Orange); Fruit (Citrus); Fruit (Deep Orange); Fruit (Other); Legumes; Nuts and Seeds; Whole Grains; Fish and Shellfish; Poultry and Game; Low-fat Dairy; Eggs; Oils (Liquid). Negative: High-fat Dairy; Red meat; Processed meat; Refined grains and baked goods; Sweets and ice cream; SSBs; Juice; White roots and tubers; Purchased deep fried foods AHEI-2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; MDD-W: Positive: Vegetables (starchy) and Grains; Vegetables (green leafy); Vegetables & Fruit Vit. A; Vegetables (Other); Fruit (Other); Nuts and Seeds; Dairy; Animal flesh; Eggs; Method(s): Index/score analysis | Follow-up duration or age: 16 y; [underlined: Body weight:]; ΔGDQS & ΔWt, 4y F/U; <−5 decrease, β: 1.03, 95% CI: 0.94, 1.11; −5 to <−2 decrease, β: 0.47, 95% CI: 0.41, 0.54; −2 to 2 little Δ, β: 1, ref; >2 to 5 increase, β: −0.44, 95% CI: −0.50, −0.38; >5 increase, β: −1.13, 95% CI: −1.19, −1.06 per 5-pt: β: −0.77, 95% CI: −0.80, −0.75; [underlined: Risk of Ob/OW:]; ΔGDQS & Ob, 4y F/U; <−5 decrease, RR: 1.32, 95% CI: 1.26, 1.37; −5 to <−2 decrease, RR: 1.13, 95% CI: 1.08, 1.17; −2 to 2 little change, RR: 1, ref; >2 to 5 increase, RR: 0.89, 95% CI: 0.86, 0.93 >5 increase, RR: 0.77, 95% CI: 0.74, 0.81; per 5-pt: RR: 0.84, 9 | - [underlined: Did not account for:] Race/Ethnicity, Anthropometry, SEP (NHS-II); - Self-reported Wt, Ht but validated; Diet change assessed Δ4y Supplemental data not available for AHEI-2010 or MDD-W and GBCO; - Additional analyses conducted by age for GDQS; Funding: FHI Solutions, Bill & Melinda Gates Foundation, NIH
Funtikova, 2014 ^112^; Spain; n/a; Analytic N=1879; Participant characteristics:; - ∼ 50–54% Female; - Mean WC, cm: T1, 89.6; T2, 89.5; T3, 89.0; p=0.387; - Abdominal Ob: T1, 30.6%; T2, 32.2%; T3, 24.9%; p=0.028; Race and/or Ethnicity: NR; SEP: Education > secondary: T1, 37.5%; T2, 34.8%; T3, 38.1%; p=0.429 | Age at Dietary Pattern: 25 to 74 y at baseline; Spain modified Mediterranean Diet (mMDS or R-MDS) [Benitez-Arciniega 2011 modified Trichopoulou 2005]; Mediterranean diet Score based on Spain dietary recommendations (MDS-rec) [Funtikova, 2014]; R-MDS: Positive (tertiles): Vegetables; Fruit; Legumes; Nuts; Cereals; Fish; Olive Oil. Negative: Meat (red meat, poultry, sausages+); Dairy Products. Neutral: Red Wine; MDS-rec: Positive (weekly/daily): Vegetables; Fruits; Legumes; Nuts; Cereals; Fish; Olive oil; Negative: Meat (red meat, poultry, sausages+); Dairy products. Neutral: Red Wine; Method(s): Index/score analysis | Follow-up duration or age: 10 y; [underlined: Waist/Central:]; 10-y ΔWC (cm); R-MDS, per-10-pt: −1.65, 95% CI: −2.84, −0.45; MDS-rec, per-10-pt: −1.49, 95% CI: −2.85, −0.13; 10-y Abdominal Ob (N=1329); R-MDS:; 1st: OR 1, ref; 2nd: OR 0.73, 95% CI: 0.52, 1.04; 3rd: OR 0.79, 95% CI: 0.55, 1.12; P-trend = 0.185; MDS-rec; 1st: OR 1, ref; 2nd: OR 1.08, 95% CI: 0.76, 1.55; 3rd: OR 0.90, 95% CI: 0.64, 1.29; P-trend=0.571 | - [underlined: Did not account for:] Race/ethnicity (likely all Spanish); - Diet assessed only once at baseline; - Did not describe or fully account for missing data; Funding: Fondo Europeo de Desarrollo Regional; Spain’s Ministerio de Sanidad y Consumo, Instituto de Salud Carlos III FEDER; Red HERACLES; National Program of University Professors Formation; Ministry of Education of Spain; Health Department of the Catalan Government
Glenn, 2021 ^116^; Spain; PREDIMED-Plus; Analytic N=6633; Participant characteristics:; - 100% OW/Ob + MetSyn 3+: BMI 27–40; ∼29% w/T2D; HTN ∼93.5%; Hypercholesteremia ∼75%;; - 0% CVD; Family Hx CVD ∼40%; Family Hx DM ∼42%; Race and/or Ethnicity: 98% Eurpoean descent; SEP: Highest education: Primary school or less, 47–52%; Complete secondary, 26–31%; University, 21–24% | Age at Dietary Pattern: 55 to 75 y at baseline; DASH Score [Fung 2008]; DASH Score: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method(s): Index/score analysis | Follow-up duration or age: 6 mo, 1 y; [underlined: BMI:]; DASH & BMI:; Q1, HR: 0, ref; Q2, HR: −0.19, 95% CI: −0.23, −0.14; Q3, HR: −0.35, 95% CI: −0.40, −0.29; Q4, HR: −0.57, 95% CI: −0.64, −0.52; p-trend<0.001; per-SD, HR: −0.25, 95% CI: −0.28, −0.23, p-trend<0.001; [underlined: Waist/Central:]; DASH & WC:; Q1, HR: 0, ref; Q2, HR: −0.45, 95% CI: −0.63, −0.28; Q3, HR: −1.00, 95% CI: −1.20, −0.81; Q4, HR: −1.64, 95% CI: −1.86, −1.43; p-trend<0.001; per-SD, HR: −0.69, 95% CI: −0.76, −0.60, p-trend<0.001 | - [underlined: Did not account for:] Race/Ethnicity; - Diet assessed repeatedly with validated FFQ during 1y F/U; Portfolio diet score data not considered due to examining only nutrients from DASH; Funding: ISCIII, European Union ERDF/ESF, European Research Council
Gomez-Donoso, 2018 food ^117^; Spain; SUN Cohort; Analytic N=11349; Participant characteristics: mean BMI ∼27 at baseline; Race and/or Ethnicity: NR; SEP: All University graduates, ∼ 5y mean college-education | Age at Dietary Pattern: 35 ± 11 y at baseline; Dietary Obesity Prevention Score (DOS) [Gomez-Donso, 2018]; DOS, Positive: Vegetables; Fruits; Legumes; Nuts; Yogurt; Fish; Vegetable-to-animal protein ratio. Negative: Red meat; Processed meat; Saturated animal fat; Refined grains; Ultra-processed foods; Sugary beverages; Alcohol: Beer and spirits; Method(s): Index/score analysis | Follow-up duration or age:9.3 y, median; [underlined: Body weight:]; DOS & ΔWt, g/y; Q1, β: 1, ref; Q2, β: −120.5, 95% CI: −197.5, −43.5; Q3, β: −81.5, 95% CI: −167.0, 4.0; Q4, β: −149.6, 95% CI: −233.8, −65.5; Q5, β: −230.5, 95% CI: −324.6, −136.4; p<0.001; DOS, rm & ΔWt g/y; Q1, β: 1, ref; Q2, β: −64.4, 95% CI: −133.9, 5.1; Q3, β: −62.5, 95% CI: −138.4, 13.5; Q4, β: −108.2, 95% CI: −184.9, −31.7; Q5, β: −193.8, 95% CI: −276.7, −111.0; p<0.001; [underlined: Risk of Ob/OW:]; DOS, baseline & OW/Ob; Q1, HR: 1, ref; Q2, HR: 0.84, 95% CI: 0.74, 0.95; Q3, HR: 0.79, 95% CI: 0.68, 0.91; Q4, HR: 0.78, 95% CI: 0.69, 0.90; Q5, HR: 0.63, 95% CI: 0.54, 0.74; p<0.001; DOS, rm & OW/Ob; Q1, HR: 1, ref; Q2, HR: 0.85, 95% CI: 0.75, 0.96; Q3, HR: 0.80, | - [underlined: Did not account for:] Race/ethnicity (mostly Spanish graduates); - Self-reported Wt; Diet assessed repeatedly with validated FFQ; Effects were not modified by sex, age, baseline BMI or PA; Results remained after sensitivity tests with tighter energy limits, over-reporters, missing > 12 FFQ-items, baseline Wt change, f/u of 10y, by age > 41 y; Funding: Spanish Government-Instituto de Salud Carlos III; European Regional Development Fund; Navarra Regional Government; the University of Navarra
Gómez-Donoso, 2019 a_Proveg ^118^; Spain; SUN Cohort; Analytic N=11554; Participant characteristics: mean BMI ∼27 at baseline; Race and/or Ethnicity: NR; SEP: All University graduates, ∼ 5y mean college-education | Dietary patterns at age(s):34.7 +/− 10.8 years y, mean at baseline; Provegetarian Food Pattern [Martinez-Gonzalez 2014]; Plant-Based Diet Index (PDI) [Satija, 2016]; Healthful PDI (hPDI) [Satija, 2016]; unhealthful PDI (uPDI), uPDI variant 1 and 2 [Satija, 2016]; Pro-vegetarian: Positive: Vegetables; Potatoes; Legumes; Fruit; Nuts; Cereals; Olive Oil. Negative: Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy Products; Animal Fats; hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Unhealthful PDI variant1: Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Unhealthful PDI variant 2: Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods;; Method(s): Index/score analysis | Follow-up duration or age:10.3 y, median; [underlined: Body weight:]; mean diff. ΔWt, g/y; Provegetarian, baseline; Q1, ref; Q2, β: −39, 95% CI: −118 to 39; Q3, β: −28, 95% CI: −115 to 58; Q4, β: −98, 95% CI: −181 to −16; Q5, β: −167, 95% CI: −249 to −84; p<0.001; Q3, HR: 0.95, 95% CI: 0.83, 1.09; Q4, HR: 0.93, 95% CI: 0.82, 1.06; Q5, HR: 0.85, 95% CI: 0.75, 0.96; p=0.014; per-2-unit, HR: 0.89, 95% CI: 0.82, 0.97; hPDI; Q1, ref; Q2, HR: 0.98, 95% CI: 0.86, 1.12 Provegetarian, repeated measures (rm); Q1, ref; Q2, β: −6, 95% CI: −70 to 57; Q3, β: −26, 95% CI: −96 to 45; Q4, β: −65, 95% CI: −133 to 2; Q5, β: −146, 95% CI: −214 to −78; p<0.001; hPDI, baseline; Q1, ref; Q2, β: −56, 95% CI: −138 to 26; Q3, β: −125, 95% CI: −212 to −38; Q4, β: −117, 95% CI: −200 to −35; Q5, β: −202, 95% CI: −294 to −110; p<0.001; hPDI, rm; Q1, ref; Q2, β: −73, 95% CI: −139 to −7; Q3, β: −130, 95% CI: −201 to −61; Q4, β: −94, 95% CI: −163 to −26; Q5, β: −200, 95% CI: −275 to −125; p<0.001; uPDI, baseline; Q1, ref; Q2, β: −19, 95% CI: −101 to 62; Q3, β: 35, 95% CI: −47 to 118; Q4, β: 28, 95% CI: −60 to 116; Q5, β: 22, 95% CI: −70 to 114; p=0.434; uPDI, rm; Q1, ref; Q2, β (difference): −3, 95% CI: −70 to 64; Q3, β: 28, 95% CI: −39 to 96; Q4, β: 24, 95% CI: −47 to 96; Q5, β: 32, 95% CI: −43 to 108; p=0.324; [underlined: Risk of Ob/OW:]; Ow/Ob; Provegetarian; Q1, ref; Q2, HR: 0.97, 95% CI: 0.85, 1.09 | - [underlined: Did not account for:] Race/Ethnicity (Spanish), Alcohol; - Self-reported Wt; Diet assessed repeatedly over time with validated FFQ for multiple DP; Ancillary analyses indicated more less-healthy plant foods compared to healthier plant foods were associated with higher Ow/Ob but results were NS compared to animal foods;; - Sensitivity analyses showed attenuated results if excluding those with >12 missing FFQ items and when only Obesity was the outcome, slight stronger association if BMI>24.5 were excluded and if f/u truncated to 10y.; Funding: Spanish Government-Instituto de Salud Carlos III, the European Regional Development Fund; Navarra Regional Government; University of Navara
Gomez-Donoso, 2019b_Adherence ^119^; Spain; SUN Cohort; Analytic N=11554; Participant characteristics: mean BMI ∼27 at baseline; Race and/or Ethnicity: NR; SEP: All University graduates, ∼ 5y mean college-education | Dietary patterns at age(s):35 y mean at baseline; Spanish Society of Community Nutrition Food Pyramid (SENC-FP) [Gomez-Donoso 2019]; SENC-FP: Recommended daily basis: Cereal grains and byproducts (preferably whole grain); fruits; vegetables; dairy; protein-rich foods (lean meat, fish & shellfish, eggs, legumes, nuts); olive oil; water. Optional, occassional, and moderate basis: Red and processed meats; sweets, salty snacks, spreadable fats; fermented alcoholic beverages; Method(s): Index/score analysis | Follow-up duration or age: 10.3 y, median; [underlined: Body weight:]; ΔWt/y (g), difference:; Q1, 0, ref; Q2, −20, 95% CI: −105, 65; Q3, −70, 95% CI: −157, 17; Q4, −122, 95% CI: −211, −34; Q5, −145, 95% CI: −238, −53; p-trend<0.001; ΔWt/y (g), absolute; Q1, 449, 95% CI: 387, 512; Q2, 429, 95% CI: 369, 490; Q3, 379, 95% CI: 319, 439; Q4, 327, 95% CI: 266, 386; Q5, 304, 95% CI: 241, 366; [underlined: Risk of Ob/OW:]; SENC-FP, single; Q1, HR: 1, ref; Q2, HR: 0.88, 95% CI: 0.78, 1.00; Q3, HR: 0.93, 95% CI: 0.82, 1.06; Q4, HR: 0.93, 95% CI: 0.81, 1.07; Q5, HR: 0.78, 95% CI: 0.67, 0.91; p-trend=0.007; SENC-FP, rm; Q1, HR: 1, ref; Q2, HR: 0.88, 95; [underlined: BMI:] average BMI differed between extreme quintiles (data NR) | - [underlined: Did not account for:] Race/Ethnicity; - Self-reported Wt, Ht; Diet assessed repeatedly with validated FFQ; No adjustment for multiple testing; Funding: Spanish Government-Instituto de Salud Carlos III, European Regional Development Fund, Navarra Regional Government, University of Navarra
Hennein, 2019 ^121^; United States; Framingham; Analytic N=1677 abdominal fat change; 1637 PAT change; Participant characteristics:; - mean BMI ∼27.4–27.6 by MDS Q1-Q4; Race and/or Ethnicity: mostly European ancestry; SEP: NR | Dietary patterns at age(s): mean±SD: 51±10 at baseline (range 19 to 92y); Alternate Med Diet Score (aMED) [Fung 2005; modified]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; AHEI2010: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:6y, median; [underlined: Adiposity:]; Δ aMED & Δ VAT, cm3; Q1: 715, 95% CI: 646, 784; Q2: 658, 95% CI: 599, 716; Q3: 631, 95% CI: 557, 704; Q4: 595, 95% CI: 533, 657; per SD: −50, 95% CI: −86, −14; p=0.007; Δ aMED &Δ SAT, cm3; Q1: 563, 95% CI: 486, 639; Q2: 535, 95% CI: 470, 600; Q3: 545, 95% CI: 464, 626; Q4: 442, 95% CI: 373, 510; per SD: −52, 95% CI: −92, −12; p=0.01; Δ aMED & Δ VSR; Q1: 0.11, 95% CI: 0.09, 0.13; Q2: 0.10, 95% CI: 0.08, 0.12; Q3: 0.09, 95% CI: 0.07, 0.11; Q4: 0.09, 95% CI: 0.07, 0.11; per SD: −0.01, 95% CI: −0.02, −0.00; p=0.04; Δ aMED & Δ PAT, cm3; Q1: 0.8, 95% CI: −4.1, 5.7; Q2: −0.4, 95% CI: −5.1, 4.3; Q3: −2.7, 95% CI: −7.5, 2.1; Q4: −1.8, 95% CI: −6.5, 2.9; per SD: −1.3, 95% CI: −2.4, −0.1; p=0.04; Δ AHEI-2010 & Δ VAT, cm3; Q1: 699, 95% CI: 632, 766; Q2: 633, 95% CI: 567, 698; Q3: 667, 95% CI: 602, 732; Q4: 571, 95% CI: 504, 638; per SD: −45, 95% CI: −79, −11; p=0.01; Δ AHEI-2010 & Δ SAT, cm3; Q1: 568, 95% CI: 496, 640; Q2: 535, 95% CI: 465, 605; Q3: 543, 95% CI: 473, 612; Q4: 420, 95% CI: 349, 492; per SD: −58, 95% CI: −95, −20; p=0.003; Δ AHEI-2010 & Δ VSR; Q1: 0.11, 95% CI: 0.09, 0.13; Q2: 0.10, 95% CI: 0.08, 0.11; Q3: 0.09, 95% CI: 0.08, 0.11; Q4: 0.09, 95% CI: 0.07, 0.11; per SD: −0.01, 95% CI: −0.02, −0.00; p=0.06; Δ AHEI-2010 & Δ PAT, cm3; Q1: 0.6, 95% CI: −1.5, 2.7; Q2: −2.1, 95% CI: −4.2, 0; Q3: −2.3, 95% CI: −4.4, −0.2; Q4: −5.8, 95% CI: −7.9, −3.7; per SD: −2.3, 95% CI: −3.4, −1.1; p<0.001 | - [underlined: Did not account for:] Race/ethnicity: European descendents; SEP; - Dietary change assessed; Outcome, i.e. adipose tissue was measured differently at two time-points and there was not adjustment/calibration between two measurements; - Sensitivity analysis showed inverse: AHEI & VAT, SAT, PAT; Funding: NHLBI; NIH; USDA; Affymetrix
Hodge, 2021 ^122^; Australia; Melbourne collaborative cohort study (MCCS); Analytic N=18414, BMI 18375, WHR; Participant characteristics:; - 43% OW; 19% Ob at baseline; 33.3% high-WHR; Race and/or Ethnicity:; - 67% Austrailian, New Zealand;; - 7% UK;; - 27% Southern European; SEP:; - SEIFA quintiles (Q1 lowest): 17%, 21%, 16%, 19%, 27% (those with higher MDS were less disadvantaged) | Dietary patterns at age(s):40 to 69 y at baseline; mean [SD] by AHEI: 54.3 [8.6]; by MDS: 54.3 [8.6]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Mediterranean Diet Score (MDS) modified [Hodge 2011]; AHEI: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; Olive Oil. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:11.6y, median; [underlined: BMI:]; AHEI & BMI; Q1, β: 1, ref; Q2, β: −0.22, 95% CI: −0.38, −0.06; p=0.006; Q3, β: −0.12, 95% CI: −0.282, 0.04; p=0.15; Q4, β: 0.232, 95% CI: −0.40, −0.07; p=0.006; Q5, β: −0.51, 95% CI: −0.68, −0.35; p<0.001; Per unit, β: −0.016, 95% CI: −0.022, 0.010; p<0.001; MDS & BMI; Score 0–3, β: 1, ref; Score 4–6, β: −0.09, 95% CI: −0.21, −0.03; p=0.12; Score 7–9, β: −0.05, 95% CI: −0.23, −0.13; p=0.56; Per unit, β: −0.019, 95% CI: −0.052, 0.013; p=0.25; [underlined: Waist/Central:]; AHEI & WHR; Q1, β: 1, ref; Q2, β: −0.004, 95% CI: −0.007, −0.002; p=0.001; Q3, β: −0.006, 95% CI: −0.008, −0.003; p<0.001; Q4, β: −0.006, 95% CI: −0.009, −0.003; p<0.001; Q5, β: −0.011, 95% CI: −0.013, −0.008; p<0.001; Per unit, β: −0.00035, 95% CI: −0.00044, −0.00026; p<0.001; MDS & WHR; Score 0–3, β: 1, ref; Score 4–6, β: −0.003, 95% CI: −0.005, −0.001; p=0.002; Score 7–9, β: −0.004, 95% CI: −0.007, −0.001; p=0.008; Per unit, β: −0.0009, 95% CI: −0.0014, −0.00036; p=0.001 | - [underlined: Did not account for:] N/A; - Diet assessed at baseline only with validated FFQ; Funding: VicHealth and Cancer Council Victoria; Australian National Health and Medical Research Council; Cancer Council Victoria; Royal Australasian College of Physicians Fellows Career Development Fellowship
Huo, 2023 ^123^; China; China Health and Nutrition Survey (CHNS); Analytic N=10013; Participant characteristics:; - Most participants with normal weight (differed by quintile); Race and/or Ethnicity: NR; SEP: data NR; Education years differed by hPDI & uPDI quintiles | Dietary patterns at age(s):18+ y at baseline (median age differed by quintile, range 46.1 to 47.8 y; Healthful PDI (hPDI)/unhealthful PDI (uPDI) [Satija, 2016]; hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Method(s): Index/score analysis | Follow-up duration or age:5y, median; [underlined: Waist/Central:]; Abdominal obesity- hPDI; Q1, HR: 1, ref; Q2, HR: 0.93, 95% CI: 0.83, 1.05; Q3, HR: 0.88, 95% CI: 0.78, 0.99; Q4, HR: 0.79, 95% CI: 0.68, 0.91; Q5, HR: 0.80, 95% CI: 0.70, 0.92; p-trend=0.004; Abdominal obesity- uPDI; Q1, HR: 1, ref; Q2, HR: 1.16, 95% CI: 1.02, 1.31; Q3, HR: 1.14, 95% CI: 1.02, 1.28; Q4, HR: 1.35, 95% CI: 1.19, 1.54; Q5, HR: 1.36, 95% CI: 1.20, 1.54; p-trend<0.001 | - [underlined: Did not account for:] Race/Ethnicity (100% Chinese), Anthropometry at baseline; - Diet assessed with 3, 24-h recalls; DP from one timepoint; Abdominal obesity was main component affecting outcome; mediation analysis showed BMI mediated 27.8% of the association between hPDI & incident MetS; 29.7% between hPDI & abdominal obesity; Funding: National Natural Science Foundation of China, National Key R&D Program of China, Science and Technology Resources Open Sharing Platform of the Shaanxi Province
Jennings, 2020 ^125^; United Kingdom; European Prospective Investigation into Cancer (EPIC): Norfolk; Analytic N=14815; Participant characteristics:; - Mean BMI, 26.4; - Family Hx osteoporosis, 4.4%; Race and/or Ethnicity: NR; SEP: NR | Dietary patterns at age(s):39 to 79 y at baseline; Mediterranean Diet Score (MDS) [Trichopolou 2003]; Alternate Med Diet Score (aMED) [Fung 2005]; MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; aMED: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:17.4 y, mean; [underlined: Adiposity:]; FFM, adjusted for BMI; aMED; Q1, M: 1.87, 95% CI: 1.86, 1.88; Q2, M: 1.88, 95% CI: 1.87, 1.89; Q3, M: 1.90, 95%CI: 1.89, 1.91; Q4, M: 1.90, 95% CI: 1.89, 1.91; Q5, M: 1.92, 95% CI: 1.91, 1.93; Q5-Q1, M: 0.05, 95% CI: 0.04, 0.06; p<0.01; *Sex-stratified results yielded similar results in each sex; MDS; Q1, M: 1.88, 95% CI: 1.87, 1.89; Q2, M: 1.89, 95% CI: 1.88, 1.90; Q3, M: 1.90, 95%CI: 1.89, 1.90; Q4, M: 1.89, 95% CI: 1.88, 1.90; Q5, M: 1.91, 95% CI: 1.90, 1.92; Q5-Q1, M: 0.03, 95% CI: 0.01,0.04; p<0.01; *Sex-stratified results yielded similar results in each sex | - [underlined: Did not account for:] Race/Ethnicity, SEP; - Diet assessed with7-d diary at one timepoint; FFM data in Supp Table 3; Note that authors report 17y f/u for incidence but also state cross-sectional study; Funding: Medical Research Council, Cancer Research UK
Johns, 2015 ^126^; Sweden; Swedish Obese Subjects Study (SOS; Analytic N=2037; Participant characteristics:; - 100% Ob (severe); >34 ♀; >38 ♂; - Mean BMI: ♂, 39.2; ♀, 41.6; Race and/or Ethnicity: NR; SEP: NR | Dietary patterns at age(s):37 to 60 y at baseline; n/a; “Energy Dense, High Sat. Fat, Low Fiber”: lower in fruit, vegetables, low-fat yogurt, cereal, wholemeal bread, meat alternative, crisp bread, and fish; Higher in chocolate, lower-fiber bread, full-fat spread, cheese, fast food, cake, white bread, candy, fatty meat, full-fat milk, pizza, crisps, soft drink, cookie, semi-skim milk, nuts, oil, hot drink, dessert, spirits, beer, jam, potatoes, lean meat, egg, low fat spread, wine, skim milk, juice, full fat yogurt, light meals; Method(s): RRR | Follow-up duration or age: 10 y; [underlined: Body weight:] β (SE): 1.71 (0.10), p<0.001; [underlined: BMI:] β (SE): 0.60 (0.03), p<0.001; [underlined: Waist/Central:] β (SE): 1.49 (0.07), p<0.001 | - [underlined: Did not account for:] Race/Ethnicity, Anthropometry, SEP (NR in figures but reported in text as adjusted for education); - Diet assessed repeatedly; Wt and Ht measured at each visit; Funding: UK Medical Research Council
Jung, 2022 ^127^; Korea; Korean Genome and Epidemiology Study (KoGES); Analytic N=6054; Participant characteristics:; - mean BMI, PDI Q1, 23.4; Q3, 23.5; Q5, 23.5; p=0.07; - WC, cm, Q1, 78.1; Q3, 78.2; Q5, 78.4; p=0.02; Race and/or Ethnicity: Korean; SEP: High school graduate (%), PDI Q1, 54.9%; Q3, 50.9%; Q5, 42.7%; p<0.0001 | Dietary patterns at age(s):40 to 69 y at baseline; modified plant-based diet index (PDI) [Satija, 2016]; PDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Pickled Vegetables; Tea/coffee; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; hPDI: Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Pickled Vegetables; Tea/coffee; Negative: Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; uPDI: Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Pickled Vegetables; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Method(s): Index/score analysis | Follow-up duration or age:9 y, median; [underlined: Waist/Central:]; Incident abdominal obesity (WC≥ 90 cm ♂; ≥ 85 cm ♀); Baseline PDI; Q1, ref HR: 1, 95% CI:; Q2, HR: 1.13 (0.97, 1.31); Q3, HR: 0.93 (0.80, 1.08); Q4, HR: 0.97 (0.83, 1.13); Q5, HR: 1.06 (0.92, 1.24); p-trend=0.990; Recent PDI; Q2, HR: 1.00 (0.86, 1.16); Q3, HR: 0.94 (0.82, 1.09); Q4, HR: 0.85 (0.73, 0.99); Q5, HR: 0.94 (0.81, 1.10); p-trend=0.119; Cum. Avg. PDI; Q2, HR: 0.74 (0.64, 0.87); Q3, HR: 0.79 (0.68, 0.90); Q4, HR: 0.66 (0.56, 0.77); Q5, HR: 0.94 (0.82, 1.08); p-trend=0.379; Baseline hPDI; Q1, ref HR: 1, 95% CI:; Q2, HR: 1.11 (0.95, 1.29); Q3, HR: 1.09 (0.93, 1.27); Q4, HR: 1.24 (1.06, 1.44); Q5, HR: 1.09 (0.94, 1.27); p-trend=0.110; Recent hPDI; Q2, HR: 0.86 (0.74, 1.00); Q3, HR: 0.82 (0.71, 0.96); Q4, HR: 0.87 (0.75, 1.01); Q5, HR: 0.97 (0.83, 1.12); p-trend=0.826; Cum. Avg. hPDI; Q2, HR: 0.77 (0.66, 0.90); Q3, HR: 0.83 (0.72, 0.97); Q4, HR: 0.86 (0.74, 1.00); Q5, HR: 0.94 (0.81, 1.09); p-trend=0.963; Baseline uPDI; Q1, ref HR:1, 95% CI; Q2, HR: 1.17 (1.00, 1.37); Q3, HR: 1.34 (1.14, 1.57); Q4, HR: 1.34 (1.14, 1.56); Q5, HR: 1.70 (1.46, 1.98); p<0.001; Recent uPDI; Q2, HR: 1.06 (0.91, 1.23); Q3, HR: 1.20 (1.02, 1.41); Q4, HR: 1.37 (1.18, 1.59); Q5, HR: 1.52 (1.30, 1.78); p<0.001; Cum. Avg. uPDI; Q2, HR: 1.06 (0.90, 1.24); Q3, HR: 1.11 (0.95, 1.30); Q4, HR: 1.15 (0.98, 1.35); Q5, HR: 1.76 (1.51, 2.06); p<0.001; Results stratified by gender: PDI & WC was NS in men or women; uPDI & WC were positively associated in men and in women, with cumulative average diet slightly stronger (than baseline or recent diet) in both men and women | - [underlined: Did not account for:] N/A; - Diet assessed repeatedly at baseline and visit 3 (comparable); Results stratified by gender: PDI & WC was NS in men or women; uPDI & WC were positively associated in men and in women, with cumulative average diet slightly stronger (than baseline or recent diet) in both men and women; Funding: National Research Institute of Health, Korea Centers for Disease Control and Prevention, and the Ministry for Health and Welfare, Republic of Korea
Kanerva, 2018 ^128^; Finland; The Dietary, Lifestyle and Genetic Determinants of Obesity and Metabolic syndrome (DILGOM); Analytic N=3735; Participant characteristics:; - Mean BMI: ♂ 26.8; ♀ 26.4;; - mean WC: ♂ 95.5; ♀ 86.0 cm; Race and/or Ethnicity: NR; SEP: Education (low; mid; high) by BSDS quintiles:; - Q1: 31.2%; 37.3%; 31.7%; - Q3: 27.2%; 34.8%; 38.0%; - Q5: 16.8%; 35.5%; 47.7% p<0.001 | Dietary patterns at age(s):25 to 75 yr; Baltic sea diet [Kanerva, 2014]; BSD, Positive: Vegetables (including legumes, not potatoes); Apples/pears/peaches plus berries; Oats/rye bread/porridge; Fatty fish; E% from fat PUFA/SFA & Trans FA; Negative: Red/Processed Meat; Neutral: Total alcohol; Method(s): Index/score analysis | Follow-up duration or age:7 y; [underlined: Body weight:]Δ Wt (kg):; baseline BSDS, −0.045 (0.025), p=0.368; Δ BSDS, −0.103 (0.030), p=0.048; Increased BSDS: −0.129 (0.045), p=0.004; Decreased/unchanged BSDS subgroup: −0.075 (0.057), p=0.186; [underlined: BMI:] Δ BMI (kg/m2):; with baseline BSDS, −0.017 (0.009), p=0.055; Δ BSDS, −0.036 (0.011), p=0.001; Increased BSDS: −0.052 (0.016), p=0.002; Decreased/unchanged BSDS: −0.024 (0.020), p=0.233; [underlined: Waist/Central:] Δ WC (cm):; with baseline BSDS, −0.026 (0.029), p=0.067; Δ BSDS, −0.059 (0.030), p=0.001; Increased BSDS: −0.089 (0.053), p=0.092; Decreased/unchanged BSDS:−0.055 (0.067), p=0.411 | - [underlined: Did not account for:] Race/ethnicity (mostly Finnish), SEP; - Self-reported Wt, Ht, BM, WC (measured); Diet change assessed over f/u; Did not describe missing data (mentioned complete cases were analysed); Sensitivity analyses (removed those with MI, stroke, T2D, Cx, or pregnancy due to potential for dietary change) shoed similar results; Funding: Finnish Foundation for Cardiovascular Research; Juho Vainio Foundation
Kang, 2021 ^129^; United States; MEC; Analytic N=53977; Participant characteristics:; - OW: ♂ 48%; ♀ 31%;; - Ob: ♂ 13%; ♀ 12%;; - BMI ≥35, ♂ 3%; ♀ 6%; Race and/or Ethnicity:; - African American, ♂ 7%; ♀ 12%;; - Native Hawaiian, ♂ 8%; ♀ 8%;; - Japanese American, ♂ 35%; ♀ 32%;; - Latino, ♂ 21%; ♀ 19%;; - White, ♂ 29%; ♀ 29%; SEP: Education:; - ≤ HS, ♂ 27%; ♀ 34%;; - Vocational/Some college, ♂ 31%; ♀ 32%;; - ≥Graduated college, ♂ 42%; ♀ 34% | Dietary patterns at age(s):45 to 70y at baseline; Healthy Eating Index (HEI-2015) [Krebs-Smith 2018]; Alternative HEI (AHEI)-2010 [Chiuve 2012]; Alternate Med Diet Score (aMED) [Fung 2005]; DASH Score [Fung 2008]; HEI-2015 - Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; PUFA+MUFA/SFA. Negative: Refined Grains; Added Sugars; SFA; Sodium AHEI-2010 - Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; aMED - Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol DASH - Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method(s): Index/score analysis | Follow-up duration or age: 10 y; [underlined: Body weight:]; ΔWt, 10-y, quintiles; HEI-2015, Stable, 1, ref; ♂ Most ↓, −0.02, 95% CI: −0.36, 0.33; ♂ Moderate ↓, 0.14, 95% CI: −0.16, 0.44; ♂ Moderate ↑, −0.39, 95% CI: −0.63, −0.14; ♂ Greatest ↑, −0.98, 95% CI: −1.21, −0.75; ♂ per-SD, −0.48, 95% CI: −0.58, −0.38; ♀ Greatest ↓, 0.79, 95% CI: 0.49, 1.10; ♀ Moderate ↓, 0.39, 95% CI: 0.11, 0.67; ♀ Moderate ↑, −0.17, 95% CI: −0.40, 0.06; ♀ Greatest ↑, −0.85, 95% CI: −1.07, −0.63; ♀ per-SD, −0.54, 95% CI: −0.63, −0.45; AHEI-2010, Stable, 1, ref; ♂ Greatest ↓, 0.51, 95% CI: 0.18, 0.83; ♂ Moderate ↓, 0.26, 95% CI: −0.03, 0.55; ♂ Moderate ↑, −0.36, 95% CI: −0.60, −0.11; ♂ Greatest ↑, −0.94, 95% CI: −1.18, −0.70; ♂ Per-SD, −0.51, 95% CI: −0.61, −0.41; ♀ Greatest ↓, 0.59, 95% CI: 0.30, 0.89; ♀ Moderate ↓, 0.30, 95% CI: 0.04, 0.57; ♀ Moderate ↑, −0.61, 95% CI: −0.84, −0.38; ♀ Greatest ↑, −0.99, 95% CI: −1.21, −0.76; ♀ per-SD, −0.58, 95% CI: −0.67, −0.49; aMED, Stable, 1, ref; ♂ Greatest ↓, 0.41, 95% CI: 0.13, 0.70; ♂ Moderate ↓, 0.44, 95% CI: 0.16, 0.71; ♂ Moderate ↑, −0.23, 95% CI: −0.49, 0.04; ♂ Greatest ↑, −0.55, 95% CI: −0.83, −0.28; ♂ Per-SD, −0.40, 95% CI: −0.51, −0.29; ♀ Greatest ↓, 0.60, 95% CI: 0.34, 0.87; ♀ Moderate =↓, 0.26, 95% CI: 0.01, 0.52; ♀ Moderate ↑,−0.16, 95% CI: −0.41,0.09; ♀ Greatest ↑, −0.62, 95% CI: −0.87, −0.37; ♀ per-SD, −0.45, 95% CI: −0.55, −0.34; DASH, Stable, 1, ref; ♂ Greatest ↓, 1.11, 95% CI: 0.75, 1.47; ♂ Moderate ↓, 0.58, 95% CI: 0.27, 0.89; ♂ Moderate ↑, −0.43, 95% CI: −0.68, −0.19; ♂ Greatest ↑, −1.17, 95% CI: −1.40, −0.93; ♂ Per-SD, −0.68, 95% CI: −0.78, −0.58; ♀ Greatest ↓,1.08, 95% CI: 0.75, 1.41; ♀ Moderate ↓, 0.28, 95% CI: −0.01, 0.57; ♀ Moderate ↑, −0.51, 95% CI: −0.74, −0.28; ♀ Greatest ↑, −1.31, 95% CI: −1.54, −1.09; ♀ per-SD, −0.74, 95% CI: −0.83, −0.64; ΔWt, 10-y, quartiles; HEI-2015, Consistently low, 1, ref; ♂ High to low, −0.06, 95% CI: −0.40, 0.27; ♂ Low to high, −0.70, 95% CI: −0.94, −0.46; ♂ Consistently high, −0.53, 95% CI: −0.75, −0.31; ♀ High to low, 0.32, 95% CI: 0.02, 0.62; ♀ Low to high, −0.79, 95% CI: −1.02, −0.57; ♀ Consistently high, −0.29, 95% CI: −0.50, −0.09; AHEI-2010, Consistently low, 1, ref; ♂ High to low, 0.13, 95% CI: −0.18, 0.43; ♂ Low to high, −0.77, 95% CI: −1.01, −0.52; ♂ Consistently high, −0.45, 95% CI: −0.67, −0.23; ♀ High to low, 0.51, 95% CI: 0.23, 0.80; ♀ Low to high, −0.62, 95% CI: −0.85, −0.39; ♀ Consistently high, −0.25, 95% CI: −0.46, −0.04; aMED, Consistently low, 1, ref; ♂ High to low, 0.03, 95% CI: −0.27, 0.34; ♂ Low to high, −0.44, 95% CI: −0.73, −0.15; ♂ Consistently high, −0.44, 95% CI: −0.70, −0.19; ♀ High to low, 0.32, 95% CI: 0.04, 0.61; ♀ Low to high, −0.39, 95% CI: −0.66, −0.12; ♀ Consistently high, −0.16, 95% CI: −0.39, 0.08; DASH, Consistently low, 1, ref; ♂ High to low, 0.36, 95% CI: 0.03, 0.69; ♂ Low to high, −0.82, 95% CI: −1.08, −0.57; ♂ Consistently high, −0.70, 95% CI: −0.93, −0.48; ♀ High to low, 1.04, 95% CI: 0.73, 1.35; ♀ Low to high, −0.51, 95% CI: −0.75, −0.26; ♀ Consistently high, −0.26, 95% CI: −0.48, −0.04 | - [underlined: Did not account for:] N/A; - Self-reported Wt, Ht, BM, WC (measured); Diet change assessed at baseline and 10y f/u; - Additional subgroup analyses conducted; - Funding: NCI; Support Program for Women in Science, Engineering, and Technology through the National Research Foundation of Korea (NRF).
Khoury, 2022 ^130^; Spain; PREDIMED Plus; Analytic N=5921; Participant characteristics:; - 48% female; 100% Ov/Ob, BMI 27–40 with ≥ 3 MetS criteria; - Mean WC, cm: ♂ 111; ♀ 104; - Mean BMI, 32.4; Race and/or Ethnicity: NR; SEP:; - 77% married, 10% widowed, 12.5% single, divorced, separated, religious;; - Education: 29% secondary (high-school), 22% University | Dietary patterns at age(s):65y, mean at baseline; Nutrient Profiling System of the British Food Standards Agency (modified version) (FSAm-NPS) score [Julia, 2014]; mFSAm-NPS, Positive: Total sugar; Saturated fats; Sodium; Energy; Negative: Vegetables, Fruits, Legumes, Nuts; Fibres and proteins; Rapeseed oil; Walnut oil; Olive Oil; Method(s): Index/score analysis | Follow-up duration or age:1 y; [underlined: BMI:]; mFSAm-NPS & BMIΔ; T1, ref β, 95% CI; T2, β: 0.27 (0.18, 0.36); T3, β: 0.51 (0.41,0.60); p-trend<0.001; Continuous, β: 0.11 (0.09, 0.13); [underlined: Waist/Central:]; mFSAm-NPS & WCΔ; T1, ref β, 95% CI; T2, β: 0.73 (0.42, 1.03); T3, β: 1.19 (0.89, 1.50); p-trend<0.001; Continuous, β: 0.28 (0.22, 0.35) | - [underlined: Did not account for:] Race/Ethnicity (100% Spanish); - Diet change assessed Δ1y from validated FFQ; Funding: Spanish Institutions for funding scientific biomedical research, CIBER Fisiopatología dela Obesidad y Nutrición (CIBEROBN) and Instituto de Salud Carlos III (ISCIII)
Kim, 2020 ^131^; Korea; Korean Genome and Epidemiology Study (KoGES); Analytic N=5646; Participant characteristics:; - PDI quintile range, mean BMI: 23.7–24; WC: 79.3–81; Race and/or Ethnicity: NR, Korean; SEP: Education, ≤6 y; 7–12y; >12y by quintile PDI:; - Q1, 18.8%; 21.9%; 59.3%; - Q2, 25.2%; 23.6%; 51.2%; - Q3, 29.5%; 21.8%; 48.7%; - Q4, 29.6%; 24.6%; 45.7%; - Q5, 35.8%; 25.2%; 39.0% | Dietary patterns at age(s):40 to 69 y at baseline; Provegetarian Food Pattern [Martinez-Gonzalez 2014]; Plant-Based Diet Index (PDI) [Satija, 2016]; Healthful PDI (hPDI) [Satija, 2016]; unhealthful PDI (uPDI) [Satija, 2016]; Pro-vegetarian: Positive: Vegetables; Potatoes; Legumes; Fruit; Nuts; Cereals; (no data on olive oil). Negative: Fish and Other Seafood; Meats and Meat Products; Eggs; Dairy Products; Animal Fats mPDI: Positive: Vegetables; Fruits and Fruit Juices; Nuts; Legumes; Whole grains; Tea/coffee; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Salty foods; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods mhPDI: Positive: Vegetables; Fruits and Fruit Juices; Nuts; Legumes; Whole grains; Tea/coffee; Negative: Salty foods; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; muPDI: Negative: Whole grains; Fruits and Fruit Juices; Vegetables; Nuts; Legumes; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Salty foods; Positive: Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Method(s): Index/score analysis | Follow-up duration or age:8 y, median; [underlined: Waist/Central:] PDI; Q1, ref; Q2, HR: 0.99, 95% CI: 0.86, 1.13; Q3, HR: 0.98, 95% CI: 0.84, 1.14; Q4, HR: 0.96, 95% CI: 0.84, 1.11; Q5, HR: 0.95, 95% CI: 0.82, 1.09; p=0.41; hPDI; Q1, ref; Q2, HR: 1.01, 95% CI: 0.87, 1.17; Q3, HR: 1.04, 95% CI: 0.91, 1.19; Q4, HR: 0.97, 95% CI: 0.83, 1.13; Q5, HR: 1.04, 95% CI: 0.89, 1.20; p=0.87; uPDI; Q1, ref; Q2, HR: 1.01, 95% CI: 0.87, 1.16; Q3, HR: 1.26, 95% CI: 1.10, 1.45; Q4, HR: 1.14, 95% CI: 0.98, 1.34; Q5, HR: 1.46, 95% CI: 1.25, 1.71; p=<0.001; Pro-vegetarian; Q1, ref; Q2, HR: 0.90, 95% CI: 0.78, 1.03; Q3, HR: 0.97, 95% CI: 0.83, 1.13; Q4, HR: 0.93, 95% CI: 0.81, 1.08; Q5, HR: 0.99, 95% CI: 0.84, 1.15; p=0.92 | - [underlined: Did not account for:] Race/Ethnicity (100% Korean); - Diet assessed at baseline and visit 3 (f/U); DP from cumulative average (or baseline if missing/MetS); - Sensitivity analyses excluding those who developed CVD or DM in f/u did not substantially change results; No data on vegetable or olive oils in this population; Funding: Ministry of Education, Science, and Technology, National Research Foundation of Korea, National Research Institute of Health, Korea Centers for Disease Control and Prevention, and the Ministry for Health and Welfare, Republic of Korea
Konieczna, 2019 ^133^; Spain; PREDIMED; Analytic N=5801; Participant characteristics:; - 100% high risk of CVD (either T2D or 3+ major risk factors at baseline); - DM: MAO, ♂ 60%; ♀ 56%; MHO, ♂ 20%; ♀ 7%; MANO, ♂ 65%; ♀ 59%; MHNO, ♂ 43%; ♀ 19% between groups, p<0.001; Race and/or Ethnicity: NR; SEP: Education (higher; secondary; primary; missing); - MAO, 11%; 21%; 67%; 1%; - MHO, 12%; 19%; 69%; 0.5%; - MANO, 14%; 21%; 64%; 1%; - MHNO, 13%; 23%; 63%; | Dietary patterns at age(s): 55 to 80 y at baseline, mean ∼ 66y; Mediterranean Diet Adherence Screener (MEDAS) [Schroder 2011]; MEDAS, Positive: Vegetables; Dishes with Tomato Sauce (tomato, garlic, onion, leek, olive oil); Pulses; Fruit; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Red Wine. Negative: Commercial Pastries; Red Meat or Sausages; Animal fat; Sugar-Sweetened Beverages; Method(s): Index/score analysis | Follow-up duration or age:5 y; [underlined: Risk of Ob/OW:]; Ob reversion; MAO -> MANO ♂ + ♀, HR 0.98, 95% CI: 0.89, 1.08; MHO -> MHNO ♂ + ♀, HR 1.04, 95% CI: 0.86, 1.26; Risk of Ob; MANO -> MAO, ♂ + ♀, HR 0.97, 95% CI: 0.84, 1.11; MHNO -> MHO, ♂ + ♀, HR 0.82, 95% CI: 0.70, 0.95 | - [underlined: Did not account for:] Race/ethnicity (Spanish); - Did not directly examine outcome; Analyzed by metabolic phenotypes; Stratification by sex showed significant inverse relationship of MEDAS with OB in ♀; Funding: CIBER de Fisiopatologia de la Obesidad y Nutricion and Instituto de Salud Carlos III, Spanish Ministry of Economy, Industry and Competitiveness and European; Social Funds (ESF), the Fundacion Instituto de Investigacion Sanitaria Illes Balears
Konieczna, 2021 ^132^; Spain; PREDIMED Plus; Analytic N=1485; Participant characteristics:; - 100% MetSyn, 3+ criteria: 75% Ob; 93% abdominal Ob; 22% T2D; 26% Depression; - mean BMI, 32.5; WC, 107.3cm; LM 56.%; FM 40.4%; Visceral fat, 2305g; Race and/or Ethnicity: White, elderly Spanish, data NR; SEP: Higher education, 21.6% | Dietary patterns at age(s):55 to 75 y at baseline; Nova “Ultra-processed” [Monteiro, 2019]; Nova 4 sub-groups: “Dairy products; Processed meat; Pre-prepared dishes; Snacks and fast-foods; Sweets; Non-alcoholic beverages; Alcoholic beverages; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age:1 y; [underlined: Adiposity:]; Visceral fat; per-10%, β: 0.09, 95% CI: 0.05, 0.13; p<0.0001; T1, ref; T2, β: 0.05, 95% CI: 0.00, 0.10; T3, β: 0.13, 95% CI: 0.07, 0.19; p<0.0001; Android-to-gynoid fat ratio; per-10%, β: 0.05, 95% CI: 0.00, 0.09; p=0.031; T1, ref; T2, β: 0.05, 95% CI: 0.00, 0.10; T3, β: 0.11, 95% CI: 0.05, 0.16; p=0.003; Total fat mass; per-10%, β: 0.09, 95% CI: 0.06, 0.13; p<0.0001; T1, ref; T2, β: 0.09, 95% CI: 0.05, 0.13; T3, β: 0.15, 95% CI: 0.11,0.19; p<0.0001 | - [underlined: Did not account for:] Race/Ethnicity (100% Spanish); - Diet assessed at baseline, 3mo, 12mo with validated FFQ;; - Sensitivity analyses: diet quality factors, adherence to ER-MedDiet; mediation analyses: extent to which nutritional variables and overall adiposity parameters might be responsible for the association between concurrent changes in UPF consumption and regional fat deposition; modification by age, T2D prevalence, smoking status, sedentary behavior, Ob; WC; Funding: European Research Council
Li, 2015 BJN ^134^; Sweden; Swedish Women’s Lifestyle and Health cohort; Analytic N=27544 for BW; 20674 for WC; Participant characteristics:; - 100% Female; - median BMI 23.0; WC 75 cm; Race and/or Ethnicity: NR; SEP: Education: ≤10 y, 27.8%; 11–13 y, 39.3%; ≥14 y, 33.0% | Dietary patterns at age(s): 29 to 49 y; 40y median at baseline; Mediterranean Diet Score (MDS) [Trichopolou 2003; cited by Couto 2013]; Healthy Nordic Food Index (HNFI) [Olsen 2011; whole grain v. rye bread as cited by Roswall, 2015]; MDS: Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish/seafood; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol NDS: Positive: Cabbage; Root Vegetables; Apples and Pears; Whole grain Bread; Oatmeal; Fish; Method(s): Index/score analysis | Follow-up duration or age: 12 y; [underlined: Body weight:]; MDS & Δ BW, kg; per 1-pt increase: β 0.03, 95% CI: −0.03, 0.09; p=0.19; 0–3: 0, ref; 4–5: 0.14, 95% CI: −0.04, 0.32; p=015; 6–9: 0.14, 95% CI: −0.08, 0.36; p=0.20; NDS & Δ BW, kg; per 1-pt: 0.04, 95% CI: −0.02, 0.10; p=0.19; 0–1: 0, ref; 2–3: 0.11, 95% CI: −0.11, 0.33; p=0.34; 4–6: 0.18, 95% CI: −0.06, 0.42; p=0.15; [underlined: Waist/Central:] ΔWC, adjusted ΔBW; MDS & ΔWC; per 1-pt: 0.02, 95% CI: −0.06, 0.10; p=0.56; 0–3: 0, ref; 4–5: 0.11, 95% CI: −0.16, 0.38; p=0.40; 6–9: −0.01, 95% CI: −0.32, 0.30; p=0.94; NDS per 1-pt: 0.06, 95% CI: −0.02, 0.14; p=0.16; 0–1: 0, ref; 2–3: 0.13, 95% CI: −0.18, 0.44; p=0.42; 4–6: 0.21, 95% CI: −0.14, 0.56; p=0.23 | - [underlined: Did not account for:] Race/ethnicity (Swedish); - Diet assessed only once at baseline; Funding: Swedish Cancer Society and the Swedish Research Council; Karolinska Institutet Distinguished Professor Award
Li, 2016 DP ^135^; China;; Analytic N=1028; Participant characteristics:; - 100% Female; - mean BMI, Low, 22.3; Middle, 22.3; High, 22.5, p=0.30; - Excluded those w Hx CVD; Race and/or Ethnicity: NR; SEP: Education (≥college): Low, 76.6%; Middle, 76.1%; High, 75.8%; p=0.96 | Dietary patterns at age(s):∼39 to 48 y; “Vegetable”: melon vegetables, starchy tubers, root vegetables, leafy and flowering vegetables, fungi and algae, lotus root, allium vegetables, fruits, fish, coarse cereals, tea, soybean, nuts, wheat, and dairy products; “Meat”: red meat, rice, poultry, and eggs; “Animal offal/dessert/alcohol”: animal offal, fish, shellfish and mollusc, condiments, convenience foods and desserts, alcohol and beverages, poultry, and red meat; Method(s): Factor/Cluster: PCA | Follow-up duration or age:3 y; [underlined: BMI:] Δ BMIz over 3 y; ‘Vegetable’; T1: 0.05, 95% CI: 0.01, 0.10; T2: 0.04, 95% CI: 0.01, 0.08; T3: 0.03, 95% CI: −0.01, 0.08; P-trend=0.51; ‘Meat’; T1: 0.02, 95% CI: −0.03, 0.06; T2: 0.09, 95% CI: 0.05, 0.13; T3: 0.02, 95% CI: −0.02, 0.07; P-trend=0.85; ‘ADA’; T1: 0.01, 95% CI: −0.04, 0.05; T2: 0.05, 95% CI: 0.01, 0.09; T3: 0.07, 95% CI: 0.03, 0.11; P-trend=0.06 | - [underlined: Did not account for:] Physical activity; - Diet from validated FFQ assessed in 2014, when outcomes were assessed (retrospective design); - Excluded men due to small sample; - Funding: National Science and Technology Support Program
Li, 2021 ^136^; China; China Nutrition and Health Survey; Analytic N=12451; Participant characteristics:; - By UPF intake: None; 1–19g/d; 20–49 g/d; ≥50 g/d; - mean BMI: 22.7; 22.8; 23.2; 23.0; p<0.001; - Mean WC: 78.9; 79.3; 80.4; 80.9, p<0.001; - OW/Ob: 21.7%; 24.1%; 26.9%; 26.2%; p<0.001; - Central obesity; 24.9%; 27.4%; 28.2%; 26.9%; p=0.070; - DM (in 2009): 9.2%; 19.4%; 13.4%; 11.1%; p=0.16; - HTN: 14.7%; 18.8%; 15.4%; 19.2%; p<0.001; Race and/or Ethnicity: NR; SEP: Income (Low, Medium, High UPF intake, g/d):; - None: 31.5%; 33.2%; 35.3%; - 1–19: 24.7%; 33.7%; 41.6%; - 20–49: 19.8%; 30.8%; 49.4%; - ≥50: 21.4%; 31.6%; 47.0%; p<0.001 | Dietary patterns at age(s):> 20 y (mean 43.7 y) at baseline; Nova “Ultra-processed” [Monteiro, 2019]; Nova 4 main sources: Instant pork-mince steam bun; Bread; Instant noodle; Cookies; Cake; Instant pork-mince dumpling; Sausage; Liquor; Soybean paste; Packaged snacks; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age: 12 y total, NR; [underlined: Risk of Ob/OW:]; 0 g/d, HR: 1, ref; 1–19 g/d, HR: 1.45, 95% CI: 1.26, 1.65; 20–49 g/d, HR: 1.34, 95% CI: 1.15, 1.57; ≥50 g/d, HR: 1.45, 95% CI: 1.21, 1.74; p<0.001; Other factors associated with overweight/obesity were age, education, urbanization (strongest), smoking, and phys; [underlined: Waist/Central:]; 0 g/d, HR: 1, ref; 1–19 g/d, HR: 1.54, 95% CI: 1.38, 1.72; 20–49 g/d, HR: 1.35, 95% CI: 1.19, 1.54; ≥50 g/d, HR: 1.50, 95% CI: 1.29, 1.74; p<0.001; Other factors associated with overweight/obesity were age, education, urbanization (strongest), smoking, and physical activity, but there were no significant interactions | - [underlined: Did not account for:] Race/Ethnicity (100% Chinese); Anthropometry; - Diet assessed repeatedly with 3, 24h-recalls; Food-processing status discussed and based on consensus e.g., ‘fruit or milk drinks’ were UPF if containing sweeteners, preservatives, or other additives’ Interactions between UPF & Ow/Ob by age, education, urbanization (strongest), smoking, and physical activity were explored but not significant; - Funding: None
Li, 2022 ^137^; Japan; Aichi Workers’ Cohort Study; Analytic N=2944; Participant characteristics:; - 48% female; - Mean BMI, 22–22.7, p<0.0001;; - WC, cm: 77.2–79.7, p<0.0001; Race and/or Ethnicity, SEP: 100% Japanese government employees, data NR; SEP: 22% higher education; 76% married | Dietary patterns at age(s):30 to 59 y at baseline; n/a; Healthy Dietary Pattern (HDP): Positive loadings (in order) for: Green vegetables, not specified; Green leafy vegetables; Dark-yellow vegetables; Tomatoes; Cooking oil; Other fruits; Mushroom; Potatoes; Soy products; Seaweed; Citrus fruits; Oily fish; Pickles; Fish products; Lean fish; Seafood other than fish; Dairy products; Salty fish; Millet; Nuts; Confectioneries; Sweeteners; Egg; Processed meats; Chicken; Bread; Mayonnaise and margarine; Miso soup; Whole-fat milk; Pasta; Low-fat milk; Noodles; Corn oil; Liver; Negative loadings for: Pork; Beef; Rice; Unhealthy Dietary Pattern (UHDP): Positive loadings (in order) for: Tomatoes; Bread; Dark-yellow; Sweeteners; Green leafy vegetables; Green vegetables, not specified; Millet; Mushroom; Vegetables, not specified; Potatoes; Seaweed; Other fruits; Citrus fruits; Confectioneries; Whole-fat milk; Pasta; Soy products; Oily fish; Corn oil; Dairy products; Egg; Chicken; Cooking oil; Mayonnaise and margarine; Low-fat milk; Lean fish; Miso soup; Salty fish; Nuts; Fish products; Pork; Processed meats; Seafood other than fish; Rice; Pickles; Method(s): RRR | Follow-up duration or age:5 y, median; [underlined: Waist/Central:]; HDP & WC; Q1, HR: 1, ref; Q2, HR: 1.10, 95% CI: 0.82, 1.47; p=0.54; Q3, HR: 1.11, 95% CI: 0.82, 1.51; p=0.48; Q4, HR: 1.04, 95% CI: 0.76, 1.43; p=0.79; p-trend=0.75; UHDP & WC; Q1, HR: 1, ref; Q2, HR: 1.37, 95% CI: 1.00, 1.86; p=0.0496; Q3, HR: 1.61, 95% CI: 1.17, 2.21; p=0.003; Q4, HR: 1.93, 95% CI: 1.42, 2.62; p<0.0001 | - [underlined: Did not account for:] Race/ethnicity; - Diet change assessed Δ1,2, 3–5y from validated FFQ; Effect modification by sex NS for CVD and T2D outcomes; - Funding: MEXT/JSPS KAKENHI; Ministry of Health Labour and Welfare; Japan Atherosclerosis Prevention Fund; Uehara Memorial Fund; Noguchi Memorial Research Institute
Lim, 2021 ^138^; Singapore; Singapore Multi-Ethnic Cohort (MEC); Analytic N=3064; Participant characteristics:; - Mean BMI: Chinese 22.8; Malay 26.2; Indian: 25.8; Race and/or Ethnicity: 52% Chinese; 23% Malay; 25% Indian; SEP: Education (Primary or <; Secondary; > Secondary); - Chinese: 18%; 38%; 45%; - Malay: 23%; 48%; 29%; - Indian: 25%; 36%; 40% | Dietary patterns at age(s): 21 to 65 y at baseline; DASH [Fung, 2008], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages AHEI-2010 [Chiuve, 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age: 6.0 y, mean; [underlined: Body weight:] ΔWt; DASH, per 5pt, β:−0.34, 95% CI: −0.55, −0.13; Q1, β:1, ref; Q2, β:−0.42, 95% CI: −0.86, 0.02; Q3, β:−0.46, 95% CI: −0.93, 0.00; Q4, β:−0.59, 95% CI: −1.11, −0.07; AHEI-2010, per 10pt, β: −0.35, 95% CI: −0.60, −0.10; Q1, β:1, ref; Q2, β:−0.24, 95% CI: −0.71, 0.24; Q3, β:−0.15, 95% CI: −0.64, 0.35; Q4, β:−0.67, 95% CI: −1.23, −0.10; [underlined: Waist/Central:] WC; DASH, per 5pt, β:−0.35, 95% CI: −0.65, −0.04, p=0.027; AHEI-2616, per 10pt, β: −0.40, 95% CI: −0.74, −0.06, p=0.021 | - [underlined: Did not account for:] N/A; - Diet change assessed over f/u; NS additional analyses by ethnicity, sex, or BMI; - Funding: National Medical Research Council, Biomedical Research Council, Ministry of Health, Singapore, National University of Singapore and National University Health System, Singapore
Liu, 2022 ^140^ China; Guizhou Population Health Cohort Study (GPHCS); Analytic N=5742; Participant characteristics:; - Mean BMI at baseline, 22.35; HTN 25.4%; DM 8.2%; [underlined: Race and/or Ethnicity]: 60.2% Han Chinese; [underlined: SEP:] Education: ≥9 y, 62.8%: <9 y, 37.2% | Dietary patterns at age(s):∼ 45 y (average); ‘High-salt and high-oil’: high factor load of fermented bean curd, bean paste, pickles, and oil; “Western”: high factor load of legumes, meat, fruits, milk, eggs, fish, and potatoes.; “Grain-vegetable’: high factor load of grains and vegetables.; “Junk food’: high factor load of beverages, desserts, and fried food; Method(s): Factor/Cluster | Follow-up duration or age: 6 to 8 y post-baseline (40,524.15 person-years); [underlined: Risk of Ob/OW:]; ‘High-salt and high-oil’ & Ob; Q1, HR: 1, ref; Q2, HR: 0.91, 95% CI: 0.70, 1.18; Q3, HR: 0.97, 95% CI: 0.74, 1.27; Q4, HR: 0.90, 95% CI: 0.69, 1.19; p=0.577; ‘Western’ & Ob; Q1, 1, ref; Q2, 0.95, 95% CI: 0.71, 1.26; Q3, 1.33, 95% CI: 1.01, 1.75; Q4, 1.21, 95% CI: | - [underlined: Did not account for:] N/A; - Diet assessed at baseline only by FFQ; - Funding: Guizhou Province Science; Technology Support Program
Liu, 2023 ^141^; United Kingdom; BIOBANK; Analytic N=27429; Participant characteristics:; - Participants with a higher sulfur microbial diet score tended to have a higher BMI, exercise less frequently, and have a lower prevalence of binge drinking compared with those with lower adherence; - Mean BMI 25.0; - Sensitivity analyses including those with CVD or cancer at baseline yielded similar direction of results for Ob/abdominal obesity; Race and/or Ethnicity: 97.1% white, 2.6% non-white; SEP: Participants with a higher sulfur microbial diet score tended to be less educated & higher HH income; - HH Income: 9.8% <18K; 20.4% 18K–30.9K; 27.8% 31K–51.9K; 26.6% 52K–100K; 7.6% >100K; - Education: 51.8% college or uni degree; 9.4% vocational qualifications; | Dietary patterns at age(s):55.3y, mean (37 to 73 y); Sulfur Microbial Diet, Positive: processed meats, bacon, hot dogs; liquor (vodka, gin); low-calorie cola, other low-energy carbonated beverages; Negative: beer; apple juice or cider, orange juice, grapefruit juice, other fruit juice; legumes (string beans, peas or lima beans, beans or lentils, tofu or soybeans, alfalfa sprouts); other vegetables (celery, mushrooms, green pepper, corn, mixed vegetables, eggplant, summer squash); chocolate bars or pieces, candy bars, cookies, brownies, doughnuts, cake, pie, sweet roll, coffee cake, pastries; Method(s): RRR: Score analysis | Follow-up duration or age:8.1y, mean; [underlined: Risk of Ob/OW:]; Ob; Q1, HR: 1.00, ref; Q2, HR: 1.15, 95% CI: 0.98, 1.35; Q3, HR: 1.25, 95% CI: 1.07, 1.46; Q4, HR: 1.44, 95% CI: 1.24, 1.67; p-trend<0.001; Per 1-SD, HR: 1.13, 95% CI: 1.07, 1.18; [underlined: Adiposity:] ≥5% BF% increase; Q1, HR: 1.00, ref; Q2, HR: 1.03, 95% CI: 0.93, 1.13; Q3, HR: 1.12, 95% CI: 1.02, 1.24; Q4, HR: 1.27, 95% CI: 1.16, 1.40; p-trend<0.001; Per 1-SD, HR: 1.08, 95% CI: 1.05, 1.12; [underlined: BMI:] ≥5% BMI increase; Q1, HR: 1.00, ref; Q2, HR: 1.04, 95% CI: 0.97, 1.13; Q3, HR: 1.06, 95% CI: 0.98, 1.15; Q4, HR: 1.13, 95% CI: 1.04, 1.22; p-trend=0.003; Per 1-SD, HR: 1.04, 95% CI: 1.01, 1.07; [underlined: Waist/Central:] Abdominal Ob.; Q1, HR: 1.00, ref; Q2, HR: 1.07, 95% CI: 0.96, 1.19; Q3, HR: 1.17, 95% CI: 1.05, 1.30; Q4, HR: 1.17, 95% CI: 1.05, 1.30; p-trend=0.002; Per 1-SD, HR: 1.05, 95% CI: 1.02, 1.09; ≥5% WC increase; Q1, HR: 1.00, ref; Q2, HR: 1.04, 95% CI: 0.98, 1.11; Q2, HR: 1.06, 95% CI: 1.00, 1.12; Q4, HR: 1.09, 95% CI: 1.03, 1.16; p-trend=0.006; Per 1-SD, HR: 1.02, 95% CI: 1.00, 1.05 | - [underlined: Did not account for:] N/A; - Diet assessed at five times with 24-h recalls and DP from cumulative average; Sensitivity analyses with further adjustment for HTN at baseline/DM at baseline/ vitamin or mineral supplement/sedentary time/‘Western’ dietary score; excluding extreme lower BMI/extreme energy intake/missing covariate data/untypical diet/<2, 24-h recalls; including those with CCD or cancer at baseline; - Funding: Central Universities of China, National Natural Science Foundation of China
Livingstone, 2022 Assoc. ^143^; United Kingdom; BIOBANK; Analytic N=17478; Participant characteristics:; - OW/Ob: 58.3%; mean baseline, BMI: 26.3; FM kg 22.8; Trunk FM kg 12.8; LM, kg: 53.7; Race and/or Ethnicity: 100% White British; SEP:; - Townsend Deprivation Index: Least, 25.8%; 2nd least, 24.2%; Mid, 20.6%; 2nd most, 17.6%; Most, 11.8% | Dietary patterns at age(s):40 to 69 y at baseline; Recommended Food Behavior Score, modified RFS [Kant 2004] (modified scoring), Positive: Tomatoes; Broccoli; Spinach; Mustard, Turnip, Collard Greens; Carrots or Mixed Vegetables and Carrots; Green Salad; Sweet Potatoes; Baked or Boiled Potatoes; Dried Beans; All fruits (Apples or Applesauce; Oranges; Grapefruits; Cantaloupe; Orange or Grapefruit Juice; Grapefruit; Other Fruit Juices; Whole grains (cooked cereals such as oatmeal); High-Fiber Cereals; Dark Breads (whole wheat, rye, pumpernickel), Corn Tortillas and Breads; Fish (baked or broiled); Lean Meats/Poultry and Alternates (baked or broiled chicken or turkey; dry beans; nuts; Low-fat or non-fat Dairy (skim, 1%, 2% milk); Removal of Chicken Skin or Fat on Red Meat; Healthy Diet Score (HDS) adapted [Maynard 2005] (modified scoring) Positive: Vegetables and Fruit; Pulses and Nuts; Fish; Dietary Fiber; Calcium. Negative: Red and Meat Products; Total Sugars; SFA; Cholesterol. Neutral: PUFA; Carbohydrates; Protein; Mediterranean Diet Score (MDS) [Trichopolou 2003] Positive: Vegetables; Legumes; Fruit, Nuts; Cereals; Fish; MUFA/SFA. Negative: Red and Processed Meat; Dairy Products. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:5.38 y, mean; [underlined: BMI:] RFS in ♂ + ♀; trunk FM, β: −0.29, 95% CI: −0.33, −0.25; p<0.001; non-linear p=0.005; total LM, β: −0.10, 95% CI: −0.14, −0.06; p<0.001; total FM, β: −0.49, 95% CI: −0.56, −0.42; p<0.001; sex p-interaction<0.001; non-linear p=0.010; HDS in ♂ + ♀; total FM, β: −0.38, 95% CI: −0.45, −0.32; p<0.001; non-linear p=0.019; trunk FM, β: −0.23, 95% CI: −0.27, −0.19; p<0.001; non-linear p=0.005; total LM, β: −0.07, 95% CI: −0.11, −0.03; p<0.001; MDS in ♂ + ♀; trunk FM, β: −0.22, 95% CI: −0.26, −0.18; p<0.001; total FM, β: −0.38, 95% CI: −0.44, −0.32; p<0.001; total LM, β: −0.07, 95% CI: −0.11, −0.04; p<0.001 | - [underlined: Did not account for:] N/A; - Diet assessed at five times with 24-h recalls and “usual baseline” DP based on average; Sex-stratified results all very similar effect size and direction to the pooled results; - Funding: National Health and Medical Research Council Emerging Leadership Fellowship; Lister Prize Fellowship; Deakin University Faculty of Health Research Capacity Building Grant Scheme
Livingstone, 2022 DP ^142^; United Kingdom; BIOBANK; Analytic N=11735; Participant characteristics:; - Mean BMI, 24.6; WC, cm, 83;; - BF%, 27.1; Race and/or Ethnicity: 100% White British; SEP:; - Education: College or university degree, 54.6%; A/AS levels, 13.3%; O levels, GCSE/CSEs, 19.8%; Professional qualifications, 8.5%; None/prefer not to answer, 3.8%; - Townsend Deprivation Index: Least 24%, 2nd least 24%, Mid 20%, 2nd Most 18%, Most 14% | Dietary patterns at age(s):40 to 69 y at baseline; DP1: higher intake of buns, cakes and pastries, confectionary and sweet biscuits; negatively associated with consumption of fruits, vegetables and low-fat yoghurt; DP2: higher intake of fruits, vegetables and buns, cakes and pastries; lower intake of butter, high-fat cheese and eggs and egg dishes; DP3: higher butter, high-fat cheese and vegetables intake; lower intake of beer and cider, wine and pasta and rice; Method(s): RRR: Response variables were discretionary foods and beverages [%E]; SFA [%E]; fiber density [g/MJ] | Follow-up duration or age:6.3 y, mean; [underlined: Risk of Ob/OW:]; Risk of Ob; DP1, HR: 1.09, 95% CI: 0.99,1.19; DP2, HR: 1.04, 95% CI: 0.95,1.14; DP3, HR: 0.96, 95% CI: 0.86,1.06; [underlined: Adiposity:]; High BF %; DP1, HR: 1.03, 95% CI: 0.98,1.08; DP2, HR: 0.99, 95% CI: 0.94,1.04; DP3, HR: 0.97, 95% CI: 0.92,1.02; [underlined: Waist/Central:]; Central Ob (WC); DP1, HR: 1.08, 95% CI: 1.03,1.14; DP2, HR: 0.99, 95% CI: 0.94,1.05; DP3, HR: 0.92, 95% CI: 0.87,0.98 | - [underlined: Did not account for:] N/A; - Diet assessed at five times with 24-h recalls and “usual baseline” DP based on average from ≥ 2; - Funding: Select authors funded by National Health and Medical Research Council Emerging Leadership Fellowship; Lister Prize Fellowship
Maskarinec, 2017 ^147^; United States; Multiethnic Cohort; Analytic N=1861; 1804 BMI; Participant characteristics:; - Mean at baseline: BMI 26.1; BF kg, 25.5; VAT area, cm2, 168; Trunk fat, kg, 13.5; muscle mass index, 7.5;; - NAFLD, 33.4%; High VAT, 52.9; Race and/or Ethnicity: 22% White, 17% African American, 16% Native American, 23% Japanese American, 21% Latino; SEP: NR | Dietary patterns at age(s): 45 to 75 y, mean 48 y at entry (∼20 y f/u); Healthy Eating Index (HEI-2010) [Guenther 2013], Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; Alternative HEI (AHEI)-2010 [Chiuve 2012] Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Alternate Med Diet Score (aMED) [Fung 2005], Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; DASH Score [Fung 2008], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method(s): Index/score analysis | Follow-up duration or age: 20.9 y, mean F/U (age ∼ 69y); [underlined: Adiposity:]; [underlined: BF, kg]; HEI-2010; T1: 25.7, 95% CI: 25.1, 26.3; T2: 25.7, 95% CI: 25.1, 26.3; T3: 24.8, 95% CI: 24.2, 25.5; per unit: −0.05, 95% CI: −0.09, −0.01; AHEI-2010; T1: 26.3, 95% CI: 25.7, 26.9; T2: 25.4, 95% CI: 24.8, 26.0; T3: 24.6, 95% CI: 24.0, 25.2; per unit: −0.08, 95% CI: −0.12, −0.04; aMED; T1: 26.0, 95% CI: 25.4, 26.6; T2: 25.7, 95% CI: 24.9, 26.5; T3: 24.7, 95% CI: 24.2, 25.3; per unit: −0.07, 95% CI: −0.12, −0.02; DASH; T1: 26.1, 95% CI: 25.5, 26.7; T2: 25.4, 95% CI: 24.8, 26.0; T3: 24.7, 95% CI: 24.1, 25.4; per unit: −0.09, 95% CI: −0.14, −0.05; Trunk fat, kg; HEI-2010; T1: 13.6, 95% CI: 13.5, 13.8; T2: 13.5, 95% CI: 13.4, 13.6; T3: 13.4, 95% CI: 13.3, 13.5; per unit: −0.02, 95% CI: −0.04, −0.01; AHEI-2010; T1: 13.6, 95% CI: 13.4, 13.7; T2: 13.5, 95% CI: 13.4, 13.6; T3: 13.4, 95% CI: 13.3, 13.5; per unit: −0.02, 95% CI: −0.03, −0.01; aMED; T1: 13.6, 95% CI: 13.5, 13.7; T2: 13.5, 95% CI: 13.3, 13.6; T3: 13.4, 95% CI: 13.3, 13.5; per unit: −0.02, 95% CI: −0.04, −0.01; DASH; T1: 13.6, 95% CI: 13.7, 13.8; T2: 13.5, 95% CI: 13.4, 13.6; T3: 13.3, 95% CI: 13.1, 13.4; per unit: −0.04, 95% CI: −0.06, −0.03; [underlined: Trunk/leg fat ratio]; HEI-2010; T1: 1.62, 95% CI: 1.58, 1.65; T2: 1.57, 95% CI: 1.54, 1.60; T3: 1.55, 95% CI: 1.52, 1.58; per unit: −0.05, 95% CI: −0.10, −0.01; AHEI-2010; T1: 1.60, 95% CI: 1.57, 1.63; T2: 1.58, 95% CI: 1.54, 1.61; T3: 1.56, 95% CI: 1.53, 1.59; per unit: −0.05, 95% CI: −0.09, −0.01; aMED; T1: 1.60, 95% CI: 1.57, 1.63; T2: 1.57, 95% CI: 1.53, 1.61; T3: 1.57, 95% CI: 1.54, 1.60; per unit: −0.03, 95% CI: −0.08, −0.01; DASH; T1: 1.64, 95% CI: 1.61, 1.67; T2: 1.55, 95% CI: 1.52, 1.59; T3: 1.53, 95% CI: 1.50, 1.57; per unit: −0.12, 95% CI: −0.17, −0.07; VAT area, m2; HEI-2010; T1: 175, 95% CI: 171, 180; T2: 169, 95% CI: 164, 173; T3: 161, 95% CI: 157, 166; per unit: −0.06, 95% CI: −0.09, −0.03; AHEI-2010; T1: 172, 95% CI: 167, 177; T2: 170, 95% CI: 166, 178; T3: 163, 95% CI: 159, 165; per unit: −0.07, 95% CI: −0.10, −0.03; aMED; T1: 173, 95% CI: 169, 178; T2: 170, 95% CI: 164, 176; T3: 163, 95% CI: 159, 168; per unit: −0.05, 95% CI: −0.08, −0.01; DASH; T1: 179, 95% CI: 174, 183; T2: 165, 95% CI: 161, 170; T3: 160, 95% CI: 155, 165; per unit: −0.11, 95% CI: −0.14, −0.07; VAT/SAT ratio; HEI-2010; T1: 0.86, 95% CI: 0.83, 0.89; T2: 0.83, 95% CI: 0.80, 0.86; T3: 0.78, 95% CI: 0.75, 0.81; per unit: −0.05, 95% CI: −0.09, −0.01; AHEI-2010; T1: 0.85, 95% CI: 0.82, 0.88; T2: 0.83, 95% CI: 0.80, 0.86; T3: 0.80, 95% CI: 0.77, 0.83; per unit: −0.06, 95% CI: −0.10, −0.03; aMED; T1: 0.84, 95% CI: 0.81, 0.87; T2: 0.83, 95% CI: 0.79, 0.87; T3: 0.81, 95% CI: 0.78, 0.83; per unit: −0.04, 95% CI: −0.08, −0.01; DASH; T1: 0.89, 95% CI: 0.86, 0.92; T2: 0.79, 95% CI: 0.76, 0.82; T3: 0.79, 95% CI: 0.75, 0.82; per unit: −0.11, 95% CI: −0.15, −0.07; % Hepatic fat; HEI-2010; T1: 6.3, 95% CI: 5.9, 6.6; T2: 5.6, 95% CI: 5.2, 5.9; T3: 5.3, 95% CI: 4.9, 5.6; per unit: −0.10, 95% CI: −0.15, −0.05; AHEI-2010; T1: 6.1, 95% CI: 5.7, 6.4; T2: 6.1, 95% CI: 5.7, 6.4; T3: 5.0, 95% CI: 4.6, 5.3; per unit: −0.11, 95% CI: −0.16, −0.07; aMED; T1: 6.0, 95% CI: 5.6, 6.3; T2: 6.0, 95% CI: 5.6, 6.4; T3: 5.3, 95% CI: 4.9, 5.6; per unit: −0.08, 95% CI: −0.13, −0.02; DASH; T1: 6.5, 95% CI: 6.2, 6.9; T2: 5.4, 95% CI: 5.0, 5.7; T3: 5.0, 95% CI: 4.7, 5.4; per unit: −0.14, 95% CI: −0.19, −0.09; % Hepatic fat by Δ HEI-2010; Low/low: 6.2%, 95% CI: 5.8%, 6.5%; Low/high: 5.9%, 95% CI: 5.4%, 6.4%; High/high: 4.8%, 95% CI: 4.5%, 5.2%; Risk of high VAT (≥150 cm2); HEI-2010; T1: OR 1, ref; T2: OR 0.68, 95% CI: 0.49, 0.92; T3: OR 0.48, 95% CI: 0.35, 0.66; AHEI-2010; T1: OR 1, ref; T2: OR 0.82, 95% CI: 0.60, 1.11; T3: OR 0.62, 95% CI: 0.46, 0.85; aMED; T1: OR 1, ref; T2: OR 1.02, 95% CI: 0.72, 1.44; T3: OR 0.65, 95% CI: 0.47, 0.90; DASH; T1: OR 1, ref; T2: OR 0.46, 95% CI: 0.34, 0.63; T3: OR 0.41, 95% CI: 0.30, 0.58; Risk of high VAT (≥150 cm2) by Δ HEI-2010; Low/low: OR 1, ref; Low/high: OR 0.72, 95% CI: 0.49, 1.05; High/low: OR 0.66, 95% CI: 0.45, 0.98; High/high: OR 0.52, 95% CI: 0.38, 0.71; [underlined: BMI:] mean BMI; HEI-2010; T1: 28.1, 95% CI: 27.7, 28.5; T2: 28.1, 95% CI: 27.7, 28.5; T3: 27.6, 95% CI: 27.2, 27.9; per unit: −0.06, 95% CI: −0.11, −0.01; AHEI-2010; T1: 28.4, 95% CI: 28.0, 28.8; T2: 28.0, 95% CI: 27.6, 28.3; T3: 27.4, 95% CI: 27.1, 27.8; per unit: −0.09, 95% CI: −0.13, −0.04; aMED; T1: 28.2, 95% CI: 27.9, 28.6; T2: 28.0, 95% CI: 27.5, 28.6; T3: 27.6, 95% CI: 27.2, 27.9; per unit: −0.08, 95% CI: −0.13, −0.03; DASH; T1: 28.4, 95% CI: 28.0, 28.7; T2: 27.8, 95% CI: 27.5, 28.2; T3: 27.5, 95% CI: 27.1, 27.9; per unit: −0.09, 95% CI: −0.16, −0.06 | - [underlined: Did not account for:] N/A; - Dietary change assesed; n/a; - Funding: NIH
Maskarinec, 2020 ^146^; United States; Adiposity Phenotype Study (APS) subset of the Multiethnic Cohort (MEC); Analytic N=1861; Participant characteristics:; - Mean at baseline: BMI 26.1; BF kg, 25.5; VAT area, cm2, 168; Trunk fat, kg, 13.5; - NAFLD, 33%; High VAT, 53%; Race and/or Ethnicity: 22% White, 17% African American, 16% Native American, 23% Japanese American, 21% Latino; SEP: NR | Dietary patterns at age(s):48.5y, mean (45 to 75y at enrollment); Healthy Eating Index (HEI-2010) [Guenther 2013], Positive: Total Vegetables; Greens and Beans; Total Fruit; Whole Fruit; Whole Grains; Seafood and Plant Proteins; Total Protein Foods; Dairy; Fatty Acids. Negative: Refined Grains; Added Sugars in “Empty Calories”; Solid Fats in “Empty Calories”; Sodium; Method(s): Index/score analysis | Follow-up duration or age:♂20.8 y, mean; ♀21.0 y, mean; [underlined: Adiposity:] High VAT Risk; ♂ Low/Low, OR: 1, ref; ♂ Low/High, OR: 0.77, 95% CI: 0.45, 1.33; ♂ High/Low, OR: 0.81, 95% CI: 0.43, 1.54; ♂ High/High, OR: 0.84, 95% CI: 0.52, 1.37; ♀ Low/Low, OR: 1, ref; ♀ Low/High, OR: 0.53, 95% CI: 0.31, 0.92; ♀ High/Low, OR: 0.52, 95% CI: 0.32, 0.87; ♀ High/High, OR: 0.39, 95% CI: 0.26, 0.59; BF; ♂ T1 (31–61), M: 23.7, 95% CI: 22.9, 24.4; ♂ T2 (61–71), M: 23.1, 95% CI: 22.3, 23.9; ♂ T3 (71–92), M: 22.3, 95% CI: 21.4, 23.2; ♂ β: −0.039; p=0.09; ♀ T1 (31–61), M: 28.7, 95% CI: 27.7, 29.7; ♀ T2 (61–71), M: 27.9, 95% CI: 27.0, 28.8; ♀ T3 (71–92), M: 26.9, 95% CI: 26.1, 27.7; ♀ β: −0.072; p=0.005; p-intx=0.57; HEI-2010 & Trunk Fat; ♂ T1 (31–61), M: 13.0, 95% CI: 12.9, 13.1; ♂ T2 (61–71), M: 12.8, 95% CI: 12.7, 13.0; ♂ T3 (71–92), M: 12.7, 95% CI: 12.5, 12.9; ♂ β: −0.007; p=0.07; ♀ T1 (31–61), M: 14.3, 95% CI: 14.1, 14.5; ♀ T2 (61–71), M: 14.2, 95% CI: 14.0, 14.4; ♀ T3 (71–92), M: 13.9, 95% CI: 13.7, 14.1; ♀ β: −0.015; p=0.005; p-intx=0.50; VAT; ♂ T1 (31–61), M: 206, 95% CI: 199, 212; ♂ T2 (61–71), M: 205, 95% CI: 197, 212; ♂ T3 (71–92), M: 192, 95% CI: 184, 200; ♂ β: −0.415; p=0.04; ♀ T1 (31–61), M: 145, 95% CI: 139, 151; ♀ T2 (61–71), M: 136, 95% CI: 131, 141; ♀ T3 (71–92), M: 126, 95% CI: 122, 131; ♀ β: −0.654; p<0.0001; p-intx=0.60; VAT/SAT Ratio; ♂ T1 (31–61), M: 1.14, 95% CI: 1.09, 1.19; ♂ T2 (61–71), M: 1.12, 95% CI: 1.07, 1.18; ♂ T3 (71–92), M: 1.05, 95% CI: 0.98, 1.11; ♂ β: −0.003; p=0.09; ♀ T1 (31–61), M: 0.59, 95% CI: 0.57, 0.62; ♀ T2 (61–71), M: 0.55, 95% CI: 0.52, 0.57; ♀ T3 (71–92), M: 0.50, 95% CI: 0.48, 0.53; ♀ β: −0.003; p<0.0001; p-intx=0.95; % Liver Fat; ♂ T1 (31–61), M: 6.13, 95% CI: 5.70, 6.56; ♂ T2 (61–71), M: 5.46, 95% CI: 4.99, 5.93; ♂ T3 (71–92), M: 5.11, 95% CI: 4.58, 5.65; ♂ β: −0.047; p=0.0005; ♀ T1 (31–61), M: 6.62, 95% CI: 6.03, 7.20; ♀ T2 (61–71), M: 5.69, 95% CI: 5.17, 6.20; ♀ T3 (71–92), M: 5.22, 95% CI: 4.74, 5.70; ♀ β: −0.052; p=0.0006; p-intx=0.61; [underlined: BMI:] BMI; ♂ T1 (31–61), M: 28.2, 95% CI: 27.7, 28.6; ♂ T2 (61–71), M: 27.8, 95% CI: 27.3, 28.3; ♂ T3 (71–92), M: 27.4, 95% CI: 26.9, 28.0; ♂ β: −0.023; p=0.11; ♀ T1 (31–61), M: 29.0, 95% CI: 28.4, 29.6; ♀ T2 (61–71), M: 28.1, 95% CI: 27.5, 28.6; ♀ T3 (71–92), M: 27.4, 95% CI: 26.8, 27.9; ♀ β: −0.063; p=0.0001; p-intx=0.10 | - [underlined: Did not account for:] SEP, Anthropometry, Smoking; - Diet assessed repeatedly: at baseline (cohort entry) and F/U (clinic visit) with FFQ was “calibrated” not validated; - Funding: NIH
Mattei, 2017 ^148^; United States; Boston Puerto Rican Health Study; Analytic N=1137 for AHEI, 1140 for AHA-DS, 1189 for DASH, 1194 for HEI, 1194 for MeDS; Participant characteristics:; - Ob: ∼47–57%; Diabetes: ∼32–42%; CVD: ∼15–26%; HTN: ∼62–74%; - Current smoker: ∼14–42%; - Physical activity score: ∼31–32; - Q5 v. Q1 AHA-DS had higher PA; - Q5 v. Q1 DASH more nonsmoke; - Q5 v. Q1 HEI had more nonsmokers, Diabetes, CVD, Ob; - Q5 v. Q1 MDS had higher Diabetes %.; Race and/or Ethnicity: 100% Peurto Rican; SEP:; - IPR: ∼1.09–1.77 (Q5 v. Q1 AHA-DS had higher IPR); - Psychological acculturation score: ∼17.1–19.5 measured with a 10-item scale; - Education > 8th grade: ∼50–64%; - Married/with partner: ∼24–37% | Dietary patterns at age(s):45 to 75 y; AHA Diet Score (AHA-DS) [Bhupathiraju 2011, Positive: Vegetables and Fruit; Variety; Whole Grains; Fish; Negative: SFA; Total fats; Trans Fat; Cholesterol; Added Sugars; Sodium; Neutral: Alcohol; Alternative HEI (AHEI)-2010 [Chiuve 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Healthy Eating Index (HEI-2005) [Guenther 2008], Positive: Total Vegetables; Dark Green/Orange Vegetables, Legumes; Total Fruit; Whole Fruit; Whole Grains; Total Grains; Meat and Beans; Milk, Yogurt, Cheese, and Soy Beverages; Healthy Oils. Negative: SFA; Solid fats, Alcohol, and Added Sugars; Sodium; Mediterranean Diet Score (MDS) [Trichopoulou 2003], Positive: Vegetables; Legumes (and beans); Fruit (and Orange juice), Nuts; Whole grains (oatmeal); Fish (traditional); MUFA/SFA (corn oil). Negative: Red and Processed Meat; Dairy Products (Whole Milk). Neutral: Alcohol (Beer); DASH diet modfied [modified Fung, 2008] Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Total dairy; Negative: Red and Processed Meat; Sweetened beverages; Sodium; Method(s): Index/score analysis | Follow-up duration or age: 2 y; [underlined: BMI:] BMI, by baseline diet z-score; AHA-DS: −0.17 (0.08), p=0.033; DASH: −0.07 (0.08), p=0.39; HEI-2005: −0.04 (0.08), p=0.63; MDS:−0.23 (0.08), p=0.005; AHEI-2010: −0.16 (0.08), p=0.039; [underlined: Waist/Central:] WC, by baseline diet z-score; AHA-DS: −0.09 (0.28), p=0.75; DASH: 0.05 (0.27), p=0.87; HEI-2005: −0.16 (0.28), p=0.56; MDS:−0.52 (0.26), p=0.048; AHEI-2010: −0.26 (0.27), p=0.33; 2y WHR, by baseline diet z-score; AHA-DS: −0.00002 (0.002), p=0.99; DASH: −0.001 (0.002), p=0.75; HEI-2005: −0.002 (0.002), p=0.44; MDS: −0.002 (0.002), p=0.22; AHEI-2010: −0.001 (0.002), p=0.67 | - [underlined: Did not account for:] N/A; - DP from validated-FFQ at baseline; - Funding: NIH, NHLBI, NIA
Mendonca, 2016 ^149^; Spain; SUN Cohort; Analytic N=8451; Participant characteristics:; - BMI: ∼22 kg/m2; Weight: ∼62–63 kg; - Smoking status: ∼20–24% current smoker, ∼25–26% former smoker; - PA: ∼22–23 MET-h/wk; TV time: ∼1.5–1.6 h/d; - Q4 v. Q1 UPF: highest BMI, more likely current smokers, and more TV time; Race and/or Ethnicity: NR; SEP: Education: ∼77–79% graduated university, ∼16–19% master or doctoral; Marital status: ∼45–48% single, ∼46–50% married | Dietary patterns at age(s):37.6 [11.0] y; Nova “Ultra-processed” [Monteiro, 2019]; Nova 4 main sources: Processed meat; Cookies; Pastries; Breakfast cereals; SSBs; Fruit drinks in bottles; Margarine; Chocolate; Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age:8.9 y median; [underlined: Risk of Ob/OW:]; Risk of Ob/OW; Q1: HR 1, ref; Q2: HR 1.15, 95%CI: 1.01, 1.32; Q3: HR 1.24, 95%CI: 1.09, 1.43; Q4: HR 1.26, 95%CI: 1.10, 1.45 | - [underlined: Did not account for:] Alcohol (Differed at baseline but not adjusted; unclear if included); Race/ethnicity (Spanish); - DP from validated-FFQ at baseline but FFQ was not designed for UPF; Funding: Carlos III Health Institute and the European Regional Development Fund, regional government of Navarra, and University of Navarra
Mirmiran, 2015 ^152^; Iran; Tehran Lipid and Glucose study; Analytic N=1123 for high WC,; Participant characteristics:; - BMI: ∼26–27 kg/m2; - Smokers: ∼12–17%; PA: ∼26–37% < 126 Met-min/wk, ∼32–27% 126–610 Met-min/wk, ∼31–37% > 610 Met-min/wk; - T3 v. T1 MDS had higher BMI at baseline. T3 v. T1 Sofi-MDS score more PA at baseline.; Race and/or Ethnicity: NR (Iranian); SEP: NR (district 13 residents) | Dietary patterns at age(s):18 to 74 y; modified Mediterranean Diet Score (mMDS) [Trichopoulou 2003]; literature Mediterranean Diet Score (LitMDS) [Sofi 2014]; mMDS: Positive: Vegetables; Legumes; Fruit; Cereals; Fish; MUFA+PUFA/SFA. Negative: Red and Processed Meat; Dairy Products. (Removed alcohol); LitMDS (Sofi-MDS): Positive: Vegetables; Legumes; Fruit and Nuts; Cereals; Fish and seafood; Olive Oil. Negative: Red and Processed Meat; Dairy Products. (Removed alcohol); Method(s): Index/score analysis | Follow-up duration or age:3 y; [underlined: Waist/Central:] High WC (≥ 90 cm for both sexes); MDS; T1: OR 1, ref; T2: OR 0.86, 95% CI: 0.54, 1.38; T3: OR 0.74, 95% CI: 0.48, 1.13; P-trend=0.56; Sofi-MDS; T1: OR 1, ref; T2: OR 1.07, 95% CI: 0.71, 1.62; T3: OR 0.84, 95% CI: 0.52, 1.33; P-trend=0.82 | - [underlined: Did not account for:] SEP; - DP from validated-FFQ at baseline; - Funding: Research institute of endocrine sciences, Shahid Beheshti university of medical sciences
Mirmiran, 2017 ^151^; Iran; Tehran Lipid and Glucose Study; Analytic N=2259; Participant characteristics:; By those w/ v. w/o CVD; - BMI (kg/m2): 28.4±4.4 v. 26.5±4.8; - WC (cm): 97.2±10.1 v. CVD: 88.0±13.2; - DM: 14% v. 4%; - HTN: 44% v. 8%; - Smoking:: 26% v. 23% (NS); - Family Hx premature CVD: 12% v. 9% (NS); Race and/or Ethnicity: NR (Iranian); SEP: district 13 residents | Dietary patterns at age(s):≥19 y; ‘Western’: High loadings for: Salty snacsks; Fast and processed foods; Mayonnaise; Soft drinks; Confectioneries; Vegetable oils; Red meats (higher than ‘Traditional’); Lower than ‘Traditional’: White meats: fish/poultry; zWhole grains; Eggs; Potato; ‘Traditional’: High loadings for Whole Grains; Vegetables; Fruit (fresh and dried); Low-fat Dairy; High-fat Dairy; Nuts and Seeds; Legumes; White meats; Red meats (lower than ‘Western’); Eggs (lower than ‘Western’); Hydrogenated oils; Fish (higher than ‘Western’); Method(s): Factor/Cluster | Follow-up duration or age:4.7 y mean ± 1.4 y; [underlined: Waist/Central:]; ‘Western’ β: −0.33, 95% CI: −0.19, 0.86; ‘Traditional’ β: −0.21, 95% CI: −0.74, 0.31 | - [underlined: Did not account for:] SEP; Race/Ethnicity (100% Iranian); - Stability of DP over time tested after 8y but diet assessed with validated FFQ at baseline; Abstract reports n=2284; Text reports n=2259; - Funding: National Research Council of the Islamic Republic of Iran; Research Institute for Endocrine Sciences of Shahid Beheshti University of Medical Sciences; Student Research Committee, Shahid Beheshti University of Medical Sciences
Mirmiran, 2023 ^150^; Iran; Tehran Lipid and Glucose Study; Analytic N=1299; Participant characteristics:; - 61% OW/Ob;; - ∼80% non-smokers; Race and/or Ethnicity: NR (Iranian); SEP: Most with 12y+ education | Dietary pattern age(s): 29 to 49 y; Nova “Ultra-processed” [Monteiro, 2019], Nova 4, 9 sub-groups: Dairy products (ice cream, chocolate milk); Processed meat (sausages, burgers, hot dogs); Pizza; Cakes and biscuits; Candies and chocolates; Mayonnaise, margarine and hydrogenated oils; Soft drinks (carbonated soft drinks); Salty snacks (potato chips and pufak); Creamy cheese; Method(s): Index/Score analysis | Follow-up duration or age: ∼6 y; [underlined: Waist/Central:] | - [underlined: Did not account for:] Race/Ethnicity (Iranian); Physical activity; Alcohol and Smoking (but most were non-users); - Diet assessed once via FFQ; Misclassification to Nova 4 from FFQ likely; - Outcomes objectively measured; - Indirect outcome of ‘metabolically unhealthy phenotype’ stratified by baseline weight status; - Funding: Shahid Beheshti University of Medical Sciences
Olstad, 2017 ^154^; Australia; The Resilience for Eating and Activity Despite Inequality study (READI); Analytic N=1242; Participant characteristics:; - 25.6% OW, 19.2% Ob; 55.2% normal/under weight; BMI, mean (SD): 25.8 (5.7); - Smoking: 52.5% never, 27.2% former, 20.3% current; - PA (h/wk), mean (SD): 24.9 (21.8); Race and/or Ethnicity: NR; SEP: 100% most disadvantaged neighbourhoods (59.7% rural, 40.3% urban); - Education: 23.2% <HS, 46.6% HS/trade/diploma, 30.1% > HS; - Marital status: 71.9% living with partner, 28.1% not living with partner | Dietary patterns age(s):18 to 46 y; adapted Austrailian Dietary Guidelines Index (aADGI) [McNaughton, 2008]; aADGI, Postive: Vegetables; Fruits; Legumes; Cereals (breads, rice, pasta, and noodles); Whole Grain Cereals; Lean Meat/Meat alternatives; Low- or reduced fat Dairy; Water more than other fluids; Negative: SFA; Total fat; Added Sugars; Extra foods; Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:5 y; [underlined: BMI:] Δ BMI; Per unit (fixed effects): −0.014, 95% CI: −0.021, −0.007; Per unit (mixed model): −0.012, 95% CI: −0.019, −0.005 | - [underlined: Did not account for:] Race/ethnicity; Total E; - DP from FFQ at baseline; Overall findings unchanged in complete case analyses; Funding: Australian National Health and Medical Research Council; Canadian Institutes of Health Research; NHMRC; Canadian; - Cancer Society Research Institute; National Health & Medical Research Council Principal Research
Otto, 2015 ^155^; United States; Multi-Ethnic Study of Atherosclerosis (MESA); Analytic N=2505; Participant characteristics:; - 40% OW; 29% Ob; Race and/or Ethnicity: 43% White 25% Black; 11.5% Chinese; 21% Hispanic; SEP: Some college: ∼60–70% of baseline cohort | Dietary patterns at age(s):62y, mean [45 to 84y]; Alternative Healthy Eating Index (AHEI) [McCullough 2000]: Positive: Vegetables (not potatoes, French fries); Fruit; Nuts and Soy Protein; Cereal Fiber; White: Red Meat Ratio; PUFA:SFA; Multi-Vitamin Use. Negative: Trans fat. Neutral: Alcohol; alternate DASH Score [Appel, 1997]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy; Negative: Red and Processed Meat; Total fat (higher MUFA/PUFA, lower SF); Sweetened beverages; Sodium; a Priori score [Sjitmsa, 2012]: Positive: Vegetables-Green; Vegetables-Yellow; Vegetables-Other; Tomatoes; Beans/Legumes; Fruit; Avocado; Nuts, Seeds; Soy Products; Whole Grains; Fish, fatty not fried; Fish, lean not fried; Poultry; Low-Fat Dairy; Beer, Wine, Liquor; Tea, Coffee. Negative: Fried potatoes; High-fat meat; Processed meat; Fried Fish; Fried Poultry; Whole-Fat Dairy; Butter; Candy; Soft drinks; Bakery Desserts; Salty Snacks. Neutral: Potatoes; Fruit Juices; Refined grains; Eggs; Shellfish; Margarine; Chocolate & Diet Soft Drinks; Meal replacements; Pickled foods; Soups, Sugar substitutes; Method(s): Index/score analysis | Follow-up duration or age:5y; [underlined: Waist/Central:] mean Δ; DASH & WC; Q1: 1.9, 95% CI: 1.4,2.4; Q2: 1.9, 95% CI: 1.3,2.4; Q3: 1.7, 95% CI: 1.2,2.2; Q4: 1.4, 95% CI: 0.7,2.0; Q5: 1.3, 95% CI: 0.6,2.0; p-trend=0.09; AHEI &WC; Q1: 1.7, 95% CI: 1.1,2.2; Q2: 1.7, 95% CI: 1.2,2.3; Q3: 1.8, 95% CI: 1.2,2.3; Q4: 1.5, 95% CI: 0.9,2.1; Q5: 1.6, 95% CI: 1.0,2.2; p-trend=0.67; APDQS; & WC; Q1: 1.6, 95% CI: 1.0,2.1; Q2: 1.9, 95% CI: 1.4,2.5; Q3: 1.8, 95% CI: 1.2,2.3; Q4: 1.7, 95% CI: 1.1,2.2; Q5: 1.3, 95% CI: 0.7,2.0; p-trend=0.50; [underlined: By race/ethnicity,] mean Δ; White; DASH; Q1: 1.5, 95% CI: 0.7,2.3; Q2: 1.0, 95% CI: 0.1,2.0; Q3: 1.9, 95% CI: 1.1,2.8; Q4: 1.7, 95% CI: 0.9,2.6; Q5: 1.4, 95% CI: 0.5,2.3; p-trend=0.81; AHEI; Q1: 1.7, 95% CI: 0.9,2.6; Q2: 1.7, 95% CI: 0.8,2.6; Q3: 1.4, 95% CI: 0.6,2.2; Q4: 1.4, 95% CI: 0.4,2.3; Q5: 1.5, 95% CI: 0.5,2.4; p-trend=0.61; APDQS; Q1: 1.3, 95% CI: 0.3,2.2; Q2: 1.6, 95% CI: 0.5,2.6; Q3: 1.9, 95% CI: 1.0,2.8; Q4: 1.6, 95% CI: 0.8,2.5; Q5: 1.4, 95% CI: 0.5,2.2; p-trend=0.94; Black; DASH; Q1: 1.9, 95% CI: 0.5,3.8; Q2: 2.2, 95% CI: 0.8,3.6; Q3: 0.9, 95% CI: −0.5,2.2; Q4: 1.4, 95% CI: −0.2,3.0; Q5: −0.1*, 95% CI: −1.7,1.5; p-trend=0.06; AHEI; Q1: 0.2, 95% CI: −1.1,1.4; Q2: 2.1, 95% CI: 0.7,3.5; Q3: 2.1, 95% CI: 0.8,3.3; Q4: 1.9, 95% CI: 0.7,3.1; Q5: 1.0, 95% CI: −0.2,2.3; p-trend=0.52; APDQS; Q1: 1.3, 95% CI: 0.3,2.2; Q2: 2.0, 95% CI: 0.7,3.3; Q3: 1.6, 95% CI: 0.2,3.0; Q4: 1.5, 95% CI: −0.1,3.0; Q5: 0.2, 95% CI: −1.5,1.9; p-trend=0.60; Hispanic; DASH; Q1: 2.7, 95% CI: 1.8,3.6; Q2: 3, 95% CI: 1.8,4.1; Q3: 2.1, 95% CI: 1.1,3.1; Q4: 0.5, 95% CI: −0.9,1.8; Q5: 2.1, 95% CI: 0.6,3.6; p-trend=0.06; AHEI; Q1: 2.9, 95% CI: 2.0,3.9; Q2: 1.8, 95% CI: 0.8,2.8; Q3: 2.3, 95% CI: 1.4,3.2; Q4: 0.8, 95% CI: −0.5,2.2; Q5: 2.1, 95% CI: 0.4,3.9; p-trend=0.12; APDQS; Q1: 2.6, 95% CI: 1.6,3.6; Q2: 2.3, 95% CI: 1.5,3.2; Q3: 1.6, 95% CI: 0.5,2.7; Q4: 1.7, 95% CI: 0.4,3.1; Q5: 2.5, 95% CI: 0.9,4.1; p-trend=0.56; Chinese; DASH; Q1: 2.0, 95% CI: 0.9,3.0; Q2: 1.6, 95% CI: 0.6,2.6; Q3: 1.5, 95% CI: 0.5,2.5; Q4: 1.3, 95% CI: −0.1,2.7; Q5: 2.3, 95% CI: 0,4.5; p-trend=0.81; AHEI; Q1: 1.9, 95% CI: 0.6,3.3; Q2: 1.5, 95% CI: 0.4,2.6; Q3: 1.3, 95% CI: 0.2,2.5; Q4: 2.3, 95% CI: 1.2,3.3; Q5: 1.3, 95% CI: 0.1,2.6; p-trend=0.79; APDQS; Q1: 2.8, 95% CI: 0.9,4.8; Q2: 1.3, 95% CI: 0.1,2.6; Q3: 1.7, 95% CI: 0.8,2.7; Q4: 1.9, 95% CI: 1.0,2.8; Q5: 1.0, 95% CI: −0.4,2.4; p-trend=0.42 | - [underlined: Did not account for:] N/A; - Diet assessed at baseline with validated FFQ; Imputed missing FFQ data; - Funding: NHLBI
Perala, 2017 ^158^; Finland; Helsinki Birth Cohort; Analytic N=1072; Participant characteristics:; - BMI: Women: ∼26.3–27.4 kg/m2; Men: ∼27.1–27.4 kg/m2; - Smokers: Women: ∼47–72% never, ∼17–24% former, ∼11 –29% current; Men: ∼15–38% never, ∼44–52% former, ∼11 –31 % current; - Leisure-time PA: Women: ∼1881–2205 MET (h/y); Men: ∼1657–2270 MET (h/y); - Participants with higher NDS were less often smokers; physically more active; more years of education; Race and/or Ethnicity: NR; SEP: Education: Women: ∼33– 52% ≤ 9 y, ∼12–22% 10–12 y, ∼36–49% ≥13 years; Men: ∼29–40% ≤ 9 y, −12–19% 10–12 y, ∼44–55% ≥13 y | Dietary patterns at age(s):∼61y at baseline; Baltic sea diet [Kanerva, 2014]; BSD, Positive: Vegetables (including legumes, not potatoes); Apples/pears/peaches plus berries; Oats/rye bread/porridge; Fatty fish; E% from fat PUFA/SFA & Trans FA; Negative: Red/Processed Meat; Neutral: Total alcohol; Method(s): Index/score analysis | Follow-up duration or age:10 y; [underlined: Adiposity:]; LM, kg; In ♀ :; Q1: 45.8 (4.4); Q2: 46.4 (4.9); Q3: 46.2 (4.4); Q4: 46.2 (4.8); per unit: 0.06, 95% CI: −0.04, 0.16; p=0.22; In ♂:; Q1: 62.5 (7.1); Q2: 63.2 (5.8); Q3: 63.7 (5.8); Q4: 63.8 (6.7); per unit: 0.11, 95% CI: −0.04, 0.26; p=0.16 | - [underlined: Did not account for:] Race/ethnicity (Helsinki birth cohort); - DP from validated-FFQ at baseline; Funding: British Heart Foundation;Finska Lakaresallskapet; Samfundet Folkhalsan; Juho Vainio Foundation; Signe and Ane Gyllenberg Foundation; The Diabetes Research Foundation; Finnish Foundation for Cardiovascular Research and EU H2020-PHC-2014-DynaHealth; Emil Aaltonen Foundation and Yrjö; - Jahnsson Foundation; the Academy of Finland
Pribisalić, 2021 ^160^; Croatia; 10,001 Dalmatians Study; Analytic N=1342; Participant characteristics:; Race and/or Ethnicity: NR; SEP: Years of Schooling (median (IQR)): 11.00 (4.00), Island of Vis; 12.00 (3.00), Island of Korcula; 12.00 (4.00), City of Split; - Subjective material status (median (IQR)): 3.00 (0.00), Island of Vis; 3.00 (1.00), Island of Korcula; 3.00 (1.00), City of Split | Dietary patterns at age(s):18 to 98 y at baseline; Mediterranean Diet Serving Score (MDSS) [Monteagudo, 2015], Positive: Vegetables, fruit, olive oil, cereals, nuts, dairy products, wine. Negative: red meat and sweets, potatoes, legumes, eggs, fish, white meat; Method(s): Index/score analysis | Follow-up duration or age: 12 y; [underlined: BMI:]; MDSS at baseline & ΔBMI, β: −0.11, 95% CI : −0.14, −0.07, p=0.001; ΔMDSS & ΔBMI, β: −0.04, 95% CI: −0.07, 0.00, p=0.041 | - [underlined: Did not account for:] N/A; - Diet assessed repeatedly by 55-item, validated FFQ at baseline and F/; Isolated population from Adriatic islands; - Funding: Medical Research Council (UK); the European Commission Framework 6 project EUROSPAN; the European Commission Framework 7 project BBMRI-LPC; the Republic of Croatia Ministry of Science, Education and Sports research grant; the Croatian Science Foundation; the Croatian National Center of Research Excellence in Personalized Healthcare; the Center of Competence in Molecular Diagnostics
Rauber, 2021 ^161^; United Kingdom; BIOBANK; Analytic N=22659; Participant characteristics:; - 52% Female;; - BMI, mean: ∼26.5–27 kg/m2 (SD ∼4.2–4.6); - Obesity: ∼18–22%; - WC, mean: ∼87.9–89.2 cm (SD ∼12.7–13.1); - Abdominal obesity: ∼23–27%; - Mean % body fat: ∼30.1–30.5% (SD ∼8.1–8.6); - PA: ∼15–18% low, ∼36–37% moderate, ∼31–37% high, ∼12–15% missing; - Smoking: ∼56–65% never, ∼30–38% previous, ∼5–6% current; - Q4 v. Q1 more likely to never smoke; lower PA; higher BMI and WC; Race and/or Ethnicity: NR; Participants from across England, Scotland, and Wales; SEP: Deprivation index: 20% Q1,20% Q2, 20% Q3, 20% Q4, 20% Q5; Q4 v.Q1 more likely to live in most deprived area | Dietary patterns at age(s):40 to 69 y at baseline; Nova “Ultra-processed” [Monteiro, 2019]; Nova 4 main sources: Snacks, desserts (33%, confectionary, pastries, packaged salty snacks); Breads (21%, bagel, buns, rolls); Ready-to-heat meals (16% frozen or shelf-stable); Beverages (15%, milk-based, soft and fruit drinks, fruit juices, alcoholic, coffee); Spreads, sauces, other (9% e.g., margarine, gravies); Cereals breakfast (6% sweetened oat/cornflake cereals); Method(s): Index/Score Analysis: UP, Nova | Follow-up duration or age:5.6 y for Ob or high WC, 5.8 y for ≥ 5% BMI or WC increases, 1.8 y for ≥ 5% BF increase; [underlined: Risk of Ob/OW:]; Ob; Q1, HR: 1, ref; Q2, HR: 1.50, 95% CI: 0.87, 2.58; Q3, HR: 1.03, 95% CI: 0.58, 1.83; Q4, HR: 1.79, 95% CI: 1.06, 3.03;; p=0.068; per 10%, HR: 1.10, 95% CI: 0.99, 1.22; [underlined: Adiposity:] ≥ 5% BF increase; Q1, HR: 1, ref; Q2, HR: 1.05, 95% CI: 0.96, 1.16; Q3, HR: 1.05, 95% CI: 0.95, 1.16; Q4, HR: 1.14, 95% CI: 1.03, 1.25;; p<0.001; per 10%, HR: 1.03, 95% CI: 1.01, 1.05; [underlined: BMI:] ≥ 5% BMI increase; Q1, HR: 1, ref; Q2, HR: 1.07, 95% CI: 0.98, 1.18; Q3, HR: 1.07, 95% CI: 0.97, 1.17; Q4, HR: 1.31, 95% CI: 1.20, 1.43;; p<0.001; [underlined: Waist/Central:] high WC; Q1, HR: 1, ref; Q2, HR: 1.17, 95% CI: 1.03, 1.34; Q3, HR: 1.21, 95% CI: 1.06, 1.38; Q4, HR: 1.30, 95% CI: 1.14, 1.48;; p<0.001; per 10%, HR: 1.06, 95% CI: 1.03, 1.08; ≥ 5% WC increase; Q1, HR: 1, ref; Q2, HR: 1.13, 95% CI: 1.05, 1.22; Q3, HR: 1.18, 95% CI: 1.10, 1.27; Q4, HR: 1.35, 95% CI: 1.25, 1.45;; p=0.014; per 10%, HR: 1.06, 95% CI: 1.05, 1.08 | - [underlined: Did not account for:] Race/Ethnicity; - Diet assessed with 24h recall; - Funding: Fundação de Amparo à Pes quisa do Estado de São Paulo (FAPESP)
Riboldi, 2022 ^163^; Brazil; ELSA-Brasil; Analytic N=9909; Participant characteristics:; - 56% female; - BMI, kg/m2: 25.8, 23.3–28.6; - WC, cm: Men: 92.9, 86.2–100.0; Women: 84.3, 77.4–92.4; - WHR: Men 0.94, 0.89–0.98; Women 0.83, 0.79–0.88; Race and/or Ethnicity: 14.42% Black, 27.7% Brown, 54.5% White; SEP: NR | Dietary patterns at age(s):35 to 74 y at baseline (median 50 y); Inflammatory Food Index (IFI) [Roboldi, 2022], Positive: Hot dogs; Processed meat; Red meat; Pork; Seafood; Diet soda; Soda; Coffee with sugar; Juice (artificial with sugar); Juice (artificial without sugar); Beer; Negative:Butter; Nuts; Wine; Pizza; Chicken meat; Fruits; Whole-grain cereal; Method(s): Index/score analysis | Follow-up duration or age:3.7 y; [underlined: Body weight:]; Wt gain ≥ 90 %ile; T1, OR: 1, ref; T2, OR: 1.14, 95% CI: 0.95, 1.37; T3, OR: 1.30, 95% CI: 1.03, 1.55; p-trend<0.001; cont., OR: 1.12, 95% CI: 1.04, 1.21 | - [underlined: Did not account for:] N/A; - Secondary analyses adjusted for baseline WC instead of BMI, dieting between visits, or removing alcohol produced similar results; - Funding: Ministry of Health (Department of Science and Technology), Ministry of Science and Technology (Financier of Studies and Projects and National Research Council)
Roswall, 2014 ^164^; Multiple: Denmark, Germany, Italy, Netherlands, United Kingdom; European Prospective Investigation into Cancer and Nutrition; Analytic N=11048 risk of Wt gain; 6548 WC, Wt Δ; Participant characteristics:; - BMI: 26.4 kg/m2 ± 4.2; - WC: 87.5cm ± 12.7; - Smoking status: 43.3% never, 34.4% former, 22.3% current; - PA: 16.0% inactive, 31.2% moderately inactive, 23.4% moderately active, 25.4% active, 4.0% unknown; Race and/or Ethnicity: NR; SEP: Education: 0.2% none, 23.7% primary, 34.76% technical, 15.7% secondary, 22.7% university, 3.0% unknown | Dietary patterns at age(s):48 y, mean at baseline; relative Mediterranean Diet Score (rMED) [Buckland 2009], Positive: Vegetables (not potatoes); Legumes; Fruit, Nuts, and Seeds (not juice); Whole Grains, Refined Flour, Pasta, Rice, Bread, Grains; Fish; Olive Oil. Negative: Total and Processed Meat. Neutral: Alcohol; Healthy Nordic Food Index (HNFI) [Olsen 2011], Positive: Cabbage; Root Vegetables; Apples and Pears; Dark Bread; Fish (Excluded Oatmeal); Method(s): Index/score analysis | Follow-up duration or age:6.8 y median; [underlined: Body weight:]; Δ Wt (kg/y):; MDS: −0.002 95% CI: −0.009, 0.005; NDS: −0.006 95% CI: −0.02, 0.008; Risk of Wt gain:; MDS, OR: 0.98 95% CI: 0.96, 1.00; NDS, OR: 0.98 95% CI: 0.93, 1.02; [underlined: Waist/Central:]; Δ WC (cm/y):; MDS: −0.01 95% CI: −0.02, −0.001; NDS: −0.008 95% CI: −0.03, 0.010; Δ WC (BMI adjusted) (cm/y); MDS: −0.008 95% CI: −0.015, −0.001; NDS: −0.01 95% CI: −0.03, 0.003 | - [underlined: Did not account for:] Race/ethnicity (meta-analyzed for heterogeneity); - DP from validated-FFQs at baseline that were country-specific; - Funding: Danish Council for Strategic Research; European Community
Rudakoff, 2022 ^165^; Brazil; Analytic N=1021; Participant characteristics:; Race and/or Ethnicity: 62% “White”, 6% “Black”, 31% “Brown”, 1% “Yellow/Oriental”; SEP: Income, $R Min. Wage (MW): <5, 34%; 5–9.9 31%; >9.9 27% | Dietary patterns at age(s):41 y,; Nova “Ultra-processed” [Monteiro, 2019], Nova 4: Sugar-sweetened beverages; Savory snacks; Dairy products; Candies; Cold meats; Cake; UP Bread; Crackers; Instant noodles; Snacks; Mayonnaise; Granola; Margarine; Distilled drinks; Method(s): Index/score analysis | Follow-up duration or age:6 months; UPF % grams; - [underlined: BMI], β: 0.02, 95% CI: 0.00, 0.04; p= 0.135; - FMI, β: 0.02, 95% CI: 0.00, 0.04; p= 0.022; - BF%, β: 0.04, 95% CI: 0.00, 0.08; p= 0.012; - Android FM, β: 0.003, 95% CI: −0.001, 0.008; p= 0.512; - Gynoid FM, β: 0.006, 95% CI: −0.002, 0.01; p= 0.147; - Android/gynoid ratio, β: 0.0001, 95% CI : −0.0004, 0.0006; p= 0.617 | - [underlined: Did not account for:] Anthropometry; Race and/or ethnicity; - Diet assessed once via FFQ; Misclassification possible due to UPF intake based on FFQ; - Outcomes objectively measured; - Funding: Coordination for the Improvement of Higher Education Personnel-Brazil, the National Council for Scientific and Technological Development; Research Support Foundation of the State of São Paulo; Teaching, Research, and Assistance Support Foundation
San-Cristobal, 2017 ^166^; Multiple European countries (7); Food4Me; Analytic N=1263; Participant characteristics:; - 57% Female; - BMI (kg/m2): 25.4 ± 4.7; - WC (m): 0.859 ± 0.136; - Smoking status: 61.8% never, 26.4% former, 11.8% smoker; - PA factor (AU): 1.521 ± 0.104; - Additional markers reported (e.g., glucose, total cholesterol); - Q3 v. Q1 MDS had lower mean BMIs, WC, and TC and greater PA; Race and/or Ethnicity: 96.9% Caucasian; SEP: NR | Dietary patterns at age(s):41 y, mean at baseline; Mediterranean Diet Adherence Screener (MEDAS) [Estruch, 2013; Papadaki, 2018], Positive: Vegetables; Fruit; Legumes; Nuts; Fish; White Meat Over Red Meat; Olive Oil; Olive Oil as Principal Cooking Fat; Wine; Sofritas [pasta/vegetable dishes with Tomato Sauce (tomato, garlic, onion, leek, olive oil)]; Negative: Sweets or Pastries; Red Meat or Sausages; Butter, maragarine; Sugar-Sweetened Beverages; Method(s): Index/score analysis | Follow-up duration or age:6 months; [underlined: BMI:] BMI, −0.217±0.044 v.−0.397±0.052; p=0.011; [underlined: Waist/Central:] WC, −0.009±0.002 v.−0.015±0.002; p=0.01 | - [underlined: Did not account for:] Anthropometry; SEP (text says occupation but NR in results table legend); - Self-reported Wt, Ht; Baseline differences in anthropometry (BMI; WC) between groups not accounted for; - Funding: European Commission under the Food, Agriculture, Fisheries and Biotechnology Theme of the 7th Framework Programme for Research and Technological Development
Satija, 2019 ^167^; United States; NHS I, NHS II, HPFS; Analytic N=46790, NHSI 59217, NHSII 20975, HPFS; Participant characteristics:; - Weight, lb: NHS: 148 ± 29; NHS2: 147 ± 33, HPFS: 179 ± 25; - BMI (kg/m2): NHS: 25 ± 4.5; NHS2: 25 ± 5.3; HPFS: 25 ± 3.1; - BMI category: NHS: 60% <25, 28% ≥25-<30, 12% ≥30; NHS2: 66% <25, 20% ≥25-<13, 12% ≥30; HPFS: 48% <25, 44% ≥25-<30, 7.6% ≥30; - Smoking: NHS: 46% never, 25% past, 19% current; NHS2: 66% never, 23% past, 12% current; HPFS: 51% never, 40% past, 9.1% current; - PA (MET/wk): NHS: 14 ± 21; NHS2: 21 ± 27; HPFS: 22 ± 30; Race and/or Ethnicity: Caucasian; SEP: NR (employees in medical field) | Dietary patterns at age(s):52 y, mean NHSI; 37 y, mean NHSII; 50 y, mean HPFS; Plant-Based Diet Index (PDI) [Satija, 2016] Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Negative: Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Healthful PDI (hPDI), Positive: Vegetables; Fruits; Nuts; Legumes; Whole grains; Vegetable oils; Tea/coffee; Negative: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; unhealthful PDI (uPDI), Negative: Whole grains; Fruits; Vegetables; Nuts; Legumes; Vegetable oils; Tea/coffee; Animal fats; Dairy; Eggs, Fish/seafood; Meat (poultry and red meat); Miscellaneous animal-based foods; Positive: Fruit juices; Sugar-sweetened beverages; Refined grains; Potatoes; Sweets/desserts; Method(s): Index/score analysis | Follow-up duration or age:20 y total, every 4y; [underlined: Body weight:]Δ Wt, lb; PDI, ♀ + ♂; Q1: 0.01, 95% CI: −0.09, 0.11; Q2: −0.02, 95% CI: −0.11, 0.07; Q3: 0, ref; Q4: −0.04, 95% CI: −0.13, 0.06; Q5: −0.19, 95% CI: −0.29, −0.10; per-SD: −0.09, 95% CI: −0.12, −0.05; hPDI, ♀ + ♂; Q1: 1.86, 95% CI: 1.76, 1.96; Q2: 0.58, 95% CI: 0.49, 0.67; Q3: 0, ref; Q4: −0.79, 95% CI: −0.88, 0.70; Q5: −2.21, 95% CI: −2.31, −2.11; per-SD: −1.50, 95% CI: −1.53, −1.46; uPDI, ♀ + ♂; Q1: −1.18, 95% CI: −1.28, −1.08; Q2: −0.34, 95% CI: −0.43, −0.24; Q3: 0, ref; Q4: 0.36, 95% CI: 0.27, 0.46; Q5: 1.01, 95% CI: 0.91, 1.11; per-SD: 0.79, 95% CI: 0.75, 0.82; Results also reported stratified by sex/cohort | - [underlined: Did not account for:] Ethnicity and SES adjusted in additional analyses; - Self-reported Wt, Ht; Diet assessed repeatedly every 4y with FFQ; Similar results shown after further adjustment of SEP and ethnicity: PDI: −0.08 lb, 95% CI: −0.11, −0.04 lb; hPDI: −1.51 lb, 95% CI: −1.54, −1.47 lb; in uPDI: 0.79 lb, 95% CI: 0.75, 0.82 lb; Magnitude stronger among Caucasians, low-CHO consumers, younger, less-active, and OW/Ob participants; - Funding: NIH, AHA
Shakeri, 2019 ^168^; Iran; Tehran Lipid/Glucose; Analytic N=2216; Participant characteristics:; - Baseline BMI: 25.9 ± 4.1; - By Q1-Q4 EDIP score; - Current smoker: ∼9–11%; - PA (MET/h/wk): ∼19–21 (SD: ∼30–32); - WC (cm): ∼88–98 (SD: ∼10–11); - Q4 v. Q1 EDIP had lower SBP, higher current smokers and HDL-C (P < 0.05). NSD in BMI, WC, DBP, FBG, TG, or PA level.; Race and/or Ethnicity: NR (Iranian); SEP: NR | Dietary patterns at age(s):40.4y, mean at baseline; Empirical dietary inflammatory pattern (EDIP): Anti-inflammatory groups: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza. Pro-inflammatory groups: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; Method(s): Index/score analysis | Follow-up duration or age:6.2 y; [underlined: Waist/Central:] High WC (≥ 95cm ♂ and ♀); Q1: OR 1, ref; Q2: OR 1.27, 95% CI: 0.94, 1.71; Q3: OR 1.29, 95% CI: 0.95, 1.76; Q4: OR 1.43, 95% CI: 1.03, 1.97; P-trend=0.046 | - [underlined: Did not account for:] Race/Ethnicity (Iranian), Alcohol (excluded for religious regions); - Diet assessed only once at baseline; - Funding: Research Institute for Endocrine Science, Shahid Beheshti University of Medical Sciences
Steffen, 2014 ^170^; United States; CARDIA; Analytic N=4713; Participant characteristics:; - BMI (kg/m2): ∼25; - WC (cm): ∼76–78; Current smoking status: ∼29–32%; PA score: ∼361–463; - Q5 v. Q1 MDS more PA, lower WC, higher HDL; other risk factors similar; Race and/or Ethnicity: ∼50% Black; 50% White; SEP: ∼45–70% of participants had above HS education; Q5 v. Q1 MDS more highly educated | Dietary patterns at age(s):18 to 30 y; modified Mediterranean Diet Score (mMDS) [Steffan, 2014 modified Trichopoulou 2005], Positive: Vegetables; Legumes; Fruit; Fruit and Vegetable Juice; Nuts; Whole Grain products; MUFA+PUFA/SFA; Fish; Coffee and tea. Negative: Red and Processed Meat; Dairy Products; Sugar-sweetend and diet beverages; Refined Grains; Snack foods; Fried vegetables; Sauces. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:25 y; [underlined: Waist/Central:]; Abdominal obesity (WC > 88cm ♀, WC > 102 cm); 1: 59.4%; 2: 40.2%; 3: 40.5%; 4: 41.7%; 5: 41.9%; P-trend < 0.001 | - [underlined: Did not account for:] Physical activity; - Did not directly examine outcome; - Funding: NIH; NHLBI;
Sweetman, 2023 ^171^; United Kingdom; BIOBANK; Analytic N=101046; Participant characteristics:; - Health status: NR; Race and/or Ethnicity: All “white” (excluded non-white individuals); SEP:; - Townsend deprivation index, mean −1.71; 20% 1 (least deprived); 20% 2; 21% 3, 20% 4, 19% 5 (most deprived); - Education: 52% higher degree; 32% any degree; 10% vocational; 6% none | Dietary patterns at age(s):57y ♀ and 55y ♂, mean; 40 to 69 y at baseline; Dietary Pattern (DP): Positive: chocolate and confectionery, butter and other animal fat spreads (primarily butter), and low-fiber bread. Negative: fresh fruit, vegetables, and high-fiber breakfast cereals.; Method(s): RRR | Follow-up duration or age:8.1y, mean; Mean Δ; aSMM (Appendicular Skeletal Muscle Mass) ♀ Q1: −0.60, 95% CI: −0.63, −0.57; ♀ Q2: −0.57, 95% CI: −0.60, −0.54; ♀ Q3: −0.50, 95% CI: −0.53, −0.46; ♀ Q4: −0.53, 95% CI: −0.57, −0.49; ♀ Q5: −0.41, 95% CI: −0.46, −0.36; ♂ Q1: −1.31, 95% CI: −1.39, −1.24; ♂ Q2: −1.26, 95% CI: −1.32, −1.19; ♂ Q3: −1.23, 95% CI: −1.29, −1.16; ♂ Q4: −1.17, 95% CI: −1.23, −1.11; ♂ Q5: −1.05, 95% CI: −1.10, −1.00; FM; ♀ Q1: −0.26, 95% CI: −0.42, −0.11; ♀ Q2: 0.08, 95% CI: −0.07, 0.24; ♀ Q3: 0.33, 95% CI: 0.16, 0.50; ♀ Q4: 0.52, 95% CI: 0.33, 0.71; ♀ Q5: 1.11, 95% CI: 0.88, 1.35; ♂ Q1: −0.09, 95% CI: −0.28, 0.10; ♂ Q2: 0.41, 95% CI: 0.23, 0.58; ♂ Q3: 0.56, 95% CI: 0.40, 0.72; ♂ Q4: 0.88, 95% CI: 0.74, 1.03; ♂Q5: 1.26, 95% CI: 1.12, 1.39; BMI:; ♀ Q1: −0.30, 95% CI: −0.38, −0.22; ♀ Q2: −0.16, 95% CI: −0.24, −0.08; ♀ Q3: −0.07, 95% CI: −0.15, 0.01; ♀ Q4: 0.02, 95% CI: −0.06, 0.11; ♀ Q5: 0.24, 95% CI: 0.16, 0.33; ♂ Q1: −0.37, 95% CI: −0.44, −0.30; ♂ Q2: −0.24, 95% CI: −0.31, −0.17; ♂ Q3: −0.11, 95% CI: −0.18, −0.04; ♂ Q4: −0.09, 95% CI: −0.15, −0.02; ♂ Q5: 0.17, 95% CI: 0.10, 0.24; Waist/Central:; ♀ Q1: 0.27, 95% CI: −0.02, 0.57; ♀ Q2: 0.39, 95% CI: 0.10, 0.67; ♀ Q3: 0.62, 95% CI: 0.33, 0.91; ♀ Q4: 1.15, 95% CI: 0.86, 1.45; ♀ Q5: 1.94, 95% CI: 1.63, 2.25; ♂ Q1: −1.06, 95% CI: −1.34, −0.78; ♂ Q2: −0.74, 95% CI: −1.02, −0.46; ♂ 63: −0.04, 95% CI: −0.31, 0.24; ♂ Q4: 0.09, 95% CI: −0.19, 0.37; ♂ Q5: 0.93, 95% CI: 0.63, 1.22 | - [underlined: Did not account for:] Alcohol; - Diet assessed with at least 2, 24h recalls; - Funding: Wellcome Trust, Medical Research Council, Department of Health, Scottish government, Northwest Regional Development Agency, Welsh assemby government, British Heart Foundation
Tabung, 2019 ^172^; United States; NHS, HPFS; Analytic N=87440 (54397 ♀; 33043 ♂); Participant characteristics:; - NHS: OW 30.1%, Ob 14.2%; HPFS: OW 45.2%; Ob 8.9%; - Wt, kg: NHS: 68.0 ± 13.2; HPFS: 81.2 ± 11.8; - BMI, mean: NHS: 25.4 ± 4.7; HPFS: 25.5 ± 3.2; - PA, MET/wk: NHS: 14.3 ± 21.9; HPFS: 20.5 ± 28.3; - Smoking: NHS: 44.2% never, 34.1% past, 21.6% current; HPFS: 45.2% never, 44.0% past, 10.8% current; Race and/or Ethnicity: NR; SEP: NR (health professionals); Selection: Excluded those >65 y at baseline, with diseases (Cx; DM; CVD;Neurodegenerative; Gastric; CKD; Lupus) at baseline, implausible/extreme/missing diet or anthropometric data. | Dietary patterns at age(s):57.1y ♀, 54.7y ♂, mean (30 to 65 y); Empirical dietary inflammatory pattern (EDIP) [Tabung, 2016]: Anti-inflammatory group: tea, coffee, dark yellow vegetables (carrots, or squash), leafy green vegetables (cabbage, spinach, or lettuce), snacks (cracker, or potato chips), fruit juice (apple juice, cantaloupe juice, orange juice, or other fruit juice), pizza; Pro-inflammatory group: processed meat (sausage), red meat (beef, or lamb), organ meat (beef, calf, or chicken liver), other fish (canned tuna, or fish), other vegetables (mixed vegetables, green pepper, cooked mushroom, eggplant, zucchini, or cucumber), refined grains (white bread, biscuit, white rice, pasta, or vermicelli), high-energy and low energy beverages (cola with sugar, carbonated beverages with sugar, fruit punch drinks), and tomatoes; Empirical dietary index for hyperinsulinemia (EDIH) [Tabung, 2016], Positive: Red meat; Processed meat; Poultry; Tomatoes; French fries, Fish (other than dark-meat fish); Low-fat dairy; Eggs; High-energy beverages (cola and other carbonated beverages with sugar, fruit drinks); Low-energy beverages; Margarine; Cream soups; Negative: Green leafy vegetables; Whole fruit; High-fat dairy products; Coffee; Wine; Method(s): Index/score analysis | Follow-up duration or age:24 y; [underlined: Body weight:]; EDIH & Wt Δ; ♀ Q1, HR: −0.65, 95% CI: −0.73, −0.57; ♀ Q2, HR: −0.29, 95% CI: −0.37, −0.22; ♀ Q3, HR: 0, ref; ♀ Q4, HR: 0.14, 95% CI: 0.06, 0.21; ♀ Q5, HR: 0.43, 95% CI: 0.36, 0.51; ♀ per-SD, HR: 0.40, 95% CI: 0.38, 0.43; ♀ p-trend<0.0001; ♂ Q1, HR: −0.60, 95% CI: −0.71, −0.49; ♂ Q2, HR: −0.25, 95% CI: −0.36, −0.14; ♂ Q3, HR: 0, ref; ♂ Q4, HR: 0.15, 95% CI: 0.05, 0.26; ♂ Q5, HR: 0.49, 95% CI: 0.38, 0.59; ♂ per-SD, HR: 0.37, 95% CI: 0.34, 0.41; ♂ p-trend<0.0001; EDIP & Wt Δ; ♀ Q1, HR:−0.29, 95% CI: −0.37, −0.21; ♀ Q2, HR: −0.18, 95% CI: −0.25, −0.10; ♀ Q3, HR: 0, ref; ♀ Q4, HR: 0.02, 95% CI: −0.10, 0.06; ♀ Q5, HR: 0.15, 95% CI: 0.07, 0.23; ♀ per-SD, HR: 0.15, 95% CI: 0.13, 0.18; ♀ p-trend<0.0001; ♂ Q1, HR:−0.19, 95% CI: −0.27, −0.07; ♂ Q2, HR: 0.08, 95% CI: −0.19, 0.03; ♂ Q3, HR: 0, ref; ♂ Q4, HR: 0.07, 95% CI: −0.04, 0.18; ♂ Q5, HR: 0.22, 95% CI: 0.11, 0.33; ♂ per-SD, HR: 0.14, 95% CI: 0.10, 0.19; ♂ p-trend<0.0001; Results were similar with or without adjusting for energy intake; Stronger associations observed in ♀ with OW/Ob (≥25), younger (< 55 y), less physically active, never smokers, and premenopausal (no difference in postmenopausal & PMH) | - [underlined: Did not account for:] Race/Ethnicity, SEP; - Self-reported Wt, Ht; Diet assessed repeatedly every 4y with FFQ; Subgroup analyses by BMI, PA, Smoking, Age < or ≥ 55y; baseline EDIP/EDIH, Postmenopausal & PNH ever v. never; Premenopausal; - Funding: NR?
Tobias, 2016 ^173^; United States; NHS II participants w/ GDM; Analytic N=3397; Participant characteristics:; - 100% women with Hx of GDM but free of CVD, cancer, and T2D; - 27.5% OW, 23.3% Ob; - Wt, kg: 71.5, SD: 17.6; - BMI, kg/m2: 26.6 SD: 6.2; - PA (MET hr per wk): 17.3, 23.7; - Smoking status: 66.4% never, 23.1% past, 10.3% current; - Family Hx of diabetes: 33.4%; Race and/or Ethnicity: 92.4% Caucasian; SEP: NR (health professionals) | Dietary patterns at age(s):38.6y, mean at baseline; Alternative HEI (AHEI)-2010 [Chiuve 2012]: Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Alternate Med Diet Score (aMED) [Fung 2005]: Positive: Vegetables (not potatoes); Legumes; Fruit; Nuts; Whole Grains; Fish; MUFA/SFA. Negative: Red and Processed Meat. Neutral: Alcohol; DASH Score [Fung 2008]: Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Method(s): Index/score analysis | Follow-up duration or age: 20 y total, every 4y; until Dx of T2D or other chronic disease; [underlined: Body weight:]; Wt gain, kg; aHEI-2010, per-SD: −1.24, 95% CI: −1.42, −1.06; Q1: 3.27; Q2: 2.48; Q3: 1.62; Q4: 1.30; Q5: 0, ref; AMED, per-SD: −0.55, 95% CI: −0.71, −0.39; Q1: 2.56; Q2: 2.12; Q3: 1.73; Q4: 1.47; Q5: 0.94; DASH, per-SD: −0.84, 95% CI: −1.02, −0.67; Q1: 2.75; Q2: 2.12; Q3: 2.08; Q4: 1.42; Q5: 0.64; All P-trends < 0.001 | - [underlined: Did not account for:] Race/ethnicity (92% Caucasian), SEP (nurses); - Self-reported Wt, Ht but highly correlated with measured-subset; Diet assessed repeatedly every 4y with FFQ; - Funding: NIH; ADA
Um, 2023 ^176^; United States; CPS-3; Analytic N=2335; Participant characteristics:; - mean BMI in 2018 & 2020: 27.5; Race and/or Ethnicity: Majority non-Latino white (76%); - White: 76%; Latino/a: 13%; Asian/Pacific Islander: 4%; Black: 3%; American Indian/Alaskan Native: 2%; Other/missing: 2%; - Change in diet quality did not differ by racial/ethnic group; SEP: Majority college-educated or higher (78%); - Less than 5% reported food insecurity; - Change in diet quality score did not differ by education or income | Dietary patterns at age(s):55.6y, mean (30 to 65 y at baseline); Diet quality (score not named) [Um, 2023] DQ score: Positive: Vegetables, fruits, whole grains. Negative: refined grains, red and processed meat, sugar-sweetened beverages, diet beverages, fruit juices (higher score indicates higher diet quality); Method(s): Index/score analysis | Follow-up duration or age: 2y; [underlined: Body weight:]; ΔDQ & Gain ≥4.5 kg: −0.40, p-trend=0.01; ΔDQ & Gain 2.25 to <4.5 kg: −0.18, p-trend=0.20; ΔDQ & Lost or gain <2.25 kg: 0.11, p-trend=0.21; ΔDQ & Lost or gain: 2.25 to <4.5 kg: 0.66, p-trend<0.0001; ΔDQ & Lost ≥4.5 kg: 1.04, p-trend<0.0001; Between weight categories, p-trend<0.0001 | - [underlined: Did not account for:] N/A; - Self-reported Wt at both times; - Changes in diet quality assessed during COVID so may be less generalizable; - Wt Δ categories based on IQR (−2.25 to +2.25 kg) and 10th and 90th percentiles (−4.5 and +4.5 kg).; - Funding: American Cancer Society
Vinke, 2020 ^178^; Netherlands; Lifelines Cohort; Analytic N=85618; Participant characteristics:; - Wt, kg: 76.3 ± 12.1; - BMI, kg/m2: 24.6 ± 2.7; - Smoking: 21.1% current, 30.6% former, 48.3% never; - PA LC-MPVA, min/wk: 205, 75–385 (median, 25th–75th %ile); Race and/or Ethnicity: 99% White, East/West European ethnicity; SEP: Education level: 26.0% low, 41.0% moderate, 33.0% high (Lower in older age groups/women). | Dietary patterns at age(s):18 to 93 y; Lifelines Diet score (LLDS) [Vinke, 2018] LLDS, Positive: Vegetables; Fruit; Legumes and Nuts; Whole Grains; Fish; Oils (and soft margarines); Unsweetened Dairy; Tea; Coffee; Negative: Red and processed meats; Sugar-sweetened beverages; Butter (and hard margarine); Method(s): Index/score analysis | Follow-up duration or age:44 mo; median (25th–75th percentile: 35–51 mo); [underlined: Body weight:]; ♂ Wt Δ; Q1, β: 0.154, 95% CI: 0.104, 0.204; Q2, β: 0.106, 95% CI: 0.058, 0.154; Q3, β: 0.092, 95% CI: 0.043, 0.142; Q4, β: 0.023, 95% CI: −0.026, 0.072; Q5, ref; ♀ Wt Δ; Q1, β: 0.118, 95% CI: 0.071, 0.164; Q2, β: 0.074, 95% CI: 0.034, 0.114; Q3, β: 0.06, 95% CI: 0.020, 0.099; Q4, β: 0.013, 95% CI: −0.024, 0.049; Q5, ref | - [underlined: Did not account for:] Race/Ethnicity (100% Dutch); - Diet assessed once at baseline with 110-FFQ; - Funding: Dutch Ministry of Health,Welfare and Sport, Dutch Ministry of Economic Affairs, University Medical Center Groningen; University of Groningen; Northern Provinces of the Netherlands
Wang, 2018 BMJ ^179^; United States; NHS, HPFS; Analytic N=14046 (8828, NHS; 5218, HPFS); Participant characteristics:; - Free from diabetes, cancer, and CVD at baseline; - BMI, kg/m2: NHS: ∼25–26 (SD: ∼5); HPFS: ∼26 (SD ∼3–4); - Wt, kg: NHS: ∼68–69 (SD: ∼13–14); HPFS: ∼81–82 (SD: ∼12–13); - PA (MET-h/wk): NHS: ∼13–15 (SD: ∼16–22); HPFS: ∼18–22 (SD: ∼21–28); - Current smoker: NHS: ∼14–19%, HPFS: ∼8–9%; Race and/or Ethnicity: European ancestry; SEP: NR (health professionals) | Dietary patterns at age(s):∼54 y, mean across DQ in NHS; ∼55 y, mean across DQ in HPFS; Alternative HEI (AHEI)-2010 [Chiuve 2012], Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; DASH Score [Fung 2008], Positive: Vegetables (not potatoes and legumes); Nuts and Legumes; Fruit and Fruit Juice; Whole Grains; Low-Fat Dairy. Negative: Red and Processed Meat; Sweetened Beverages; Sodium; Alternate Mediterranean Diet Score (AMED) [Fung, 2005], AMED: Positive: Vegetables; Legumes; Fruit, Nuts; Whole grains; Fish; MUFA/SFA. Negative: Red and Processed Meat; Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age:20 y; [underlined: Body weight:]; Δ AHEI-2010, per SD & Δ Wt; ♀ : −0.43 (0.03); ♂ : −0.37 (0.03); ♀ + ♂: −0.40 (0.02); Δ DASH, per SD & Δ Wt; ♀ : −0.44 (0.03); ♂ : −0.39 (0.03); ♀ + ♂: −0.42 (0.02); Δ aMED, per SD & Δ Wt; ♀ : −0.12 (0.03); ♂ : −0.15 (0.03); ♀ + ♂: −0.14 (0.02); [underlined: BMI:]; Δ AHEI-2010, per SD & Δ BMI; ♀ : −0.17 (0.01); ♂: −0.12 (0.01); ♀ + ♂: −0.15 (0.01); Δ DASH, per SD & Δ BMI; ♀: −0.17 (0.01); ♂ : −0.13 (0.01); ♀ + ♂: −0.15 (0.01); Δ AMED, per SD & Δ BMI; ♀ : −0.05 (0.01); ♂ : −0.05 (0.01); ♀ + ♂: −0.05 (0.01) | - [underlined: Did not account for:] Race/ethnicity (European-descent); SEP (although nurses/physicians); - Self-reported Wt, Ht used to calculate BMI but validated against measured subset and captured change in BMI over multiple assessments; Results in Supplemental Tables C and D; - Sensitivity analysis: Similar results in those < 65 y and non-smokers (AHEI-2010, DASH, and AMED scores were inversely related to BMI change); - Funding: NIH; NHLBI; NIDDK; National Eye Institue; National Human Genome Research Institute; National Natural Science Foundation of China; AHA
Winkvist, 2017 ^180^; Sweden; Vasterbotten Intervention Programme; Analytic N=15995; Participant characteristics:; - Wt, kg: ♀ 68.8 ± 12.4; Men: 83.8 ± 11.9; - BMI, kg/m2: ♀ 25.1 ± 4.3; ♂: 26.1 ± 3.3; - PA: ♀ 17.2% inactive, 34% moderately inactive, 28% moderately active, 21% active; ♂: 19% inactive, 33% moderately inactive, 29% moderately active, 20% active; - Smoking: ♀ 22% smoker, 32% ex, 47% never; ♂: 18% smoker, 32% ex, 50% never; - TC, TG, and BP also reported; Race and/or Ethnicity: NR; All living in Vasterbotten County northern Sweden; SEP: Education: 64.8% ≤ secondary school, 35.2% academic education | Dietary patterns at age(s):45y, mean at baseline; Healthy Diet Score [Nettleton, 2013] HDS, Positive: Vegetables (not potatoes); Fruit (not juices); Whole Grains; Fish. Negative: Red and Processed Meat; Sweets and desserts; Sugar-sweetened beverages; Fried Potatoes; Method(s): Index/score analysis | Follow-up duration or age: 10 y (±1y); [underlined: BMI:]; ♀ HDS & BMI: −0.42 (0.06); ♂ HDS & BMI: −0.31 (0.05) | - [underlined: Did not account for:] Race/ethnicity (Swedish), Alcohol, Total energy; - Diet change assessed Δ10y with validated FFQ; Sensitivity analysis: similar results from adjusting baseline BMI for TC, TG and SBPs (data not shown); - Attenuated association when adjusting for 10y ΔBMI of HDS on TC (p=0.24), TG (p=0.074) and SBP (p=0.35) in women; - Funding: Swedish Council for Working Life and Social Research; the Swedish Cancer Society; the Swedish Research Council; the Wallenberg Foundation; and the Vasterbotten County Council, Sweden
Xu, 2021 ^181^; Australia; 45 and Up Study; Analytic N=69990; Participant characteristics:; - CVD, 16%; Ob 27%; OW 38%;; Race and/or Ethnicity: NR; SEP: Low: 31%, Medium 34%, High 35% via SEIFA; Education, Low: 32%, Med. 42%, High 26%; Marital status: Married/Partner 78%; Single/Divorced/Separated 14%; Widowed 7% | Dietary patterns at age(s):≥ 50 y (77% 51–70y; 23% >70y) at baseline; Score based on Asutrailan Dietary Guidelines (not named) [Xu, 2021] ADG score: Positive: Vegetables; Fruit; Grains; Meat, lean; Poultry; Seafood; Dairy. Negative > 10 standard drinks/wk; Method(s): Index/score analysis | Follow-up duration or age:6y; [underlined: Risk of Ob/OW:]; Healthy (ADG score < mean) & risk of Ob, IRR: 1, ref; Unhealthy (ADG score > mean) & risk of Ob, IRR: 1.10, 95% CI: 1.02, 1.18 | - [underlined: Did not account for:] Race/Ethnicity or Anthropometry at baseline; - Self-reported Wt, Ht; - Funding: University of Technology Sydney
Yang, 2022 ^182^; United States; NHS II; Analytic N=54062; Participant characteristics:; - 5.3% of total sample w/ Hx of GDM; - Family Hx of DM: ∼35–51%; Race and/or Ethnicity: ∼ 98% White; SEP: ∼ 95% married | Dietary patterns at age(s):40 y at baseline; Alternative HEI (AHEI)-2010 [Chiuve 2012] AHEI-2010, Positive: Vegetables (not potatoes, French fries); Fruit; Legumes and Nuts; Whole Grains; Long-Chain Fats (EPA + DHA); PUFA. Negative: Red and Processed Meat; Sugar Sweetened Beverages and Fruit Juice; Trans FA; Sodium. Neutral: Alcohol; Method(s): Index/score analysis | Follow-up duration or age: 13.4 y (mean); [underlined: Body weight:]; 4y ΔAHEI & ΔWt in mean kg; No hx of GDM; Low to high: −1.19, 95% CI: −1.41, −0.96; Low to medium: 0.55, 95% CI: 0.45, 0.66; Medium to high: 0.21, 95% CI: 0.12, 0.31; Stay high: 1.02, 95% CI: 0.98, 1.07; Stay medium: 1.41, 95% CI: 1.35, 1.48; Stay low: 1.73, 95% CI: 1.68, 1.79; Medium to low: 2.34, 95% CI: 2.24, 2.44; High to medium: 2.13, 95% CI: 2.04, 2.23; High to low: 3.41, 95% CI: 3.16, 3.66; p<0.001; Hx of GDM; Low to high: −2.97, 95% CI: −4.34, −1.60; Low to medium: −0.43, 95% CI: −1.00, 0.14; Medium to high:−0.07, 95% CI: −0.57, 0.42; Stay high: 0.68, 95% CI: 0.44, 0.93; Stay medium: 1.04, 95% CI: 0.68, 1.39; Stay low: 1.78, 95% CI: 1.51, 2.05; Medium to low: 2.49, 95% CI: 2.00, 2.99; High to medium: 2.17, 95% CI: 1.70, 2.63; High to low: 4.01, 95% CI: 2.78, 5.23; p<0.001; p-heterogeneity=0.04 | - [underlined: Did not account for:] N/A; - Self-reported Wt and Height but highly correlated with measured-subset;; - Diet assessed repeatedly every 4y with FFQ; Sensitivity analyses by BMI ≥25, Hx of GDM; - Funding: NIH, PhD program in Population Health Sciences at Harvard University, ADA

a Abbreviations: BF, Body fat (total unless specified as trunk, gynoid, android, etc.);BF%, Body fat percentage; DM, Diabetes (T1, T2); FFM, Fat-free mass; FFMI, Fat-free mass index; FM, Fat mass (total, unless specified as trunk, gynoid, android, etc.); FMI, Fat mass index; F/U, Follow-up; GDM, gestational diabetes mellitus; Hip-C, hip circumference; HS_; _high school; HTN, hypertension; Hx, History; ITT, intent-to-treat; N/A, Not applicable; NR, not reported; NS, not statistically significant Ob, Obesity; OW, Overweight; PA, Physical activity; PP, per-protocol SEP/SES, Socioeconomic position/status; T2D, Type 2 Diabetes; TC, total cholesterol; TG, triglyceride; Tx, Treatment; WC, waist circumference ^a^ WHR, waist-hip ratio; Wt, Body weight

Table 17 Risk of bias for observational studies examining the relationship between dietary patterns consumed by adults and older adults and body composition and risk of obesity^a^

Article | Confounding | Exposure classification | Participant Selection | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall
Agnoli, 2018^77^ | High | Low | Some concerns | Low | High | Some concerns | High | High
Aljadani, 2020 ^79^ | Some concerns | Low | Low | Low | Low | High | High | High
Aljadani, 2020^78^ | High | Low | Some concerns | Low | High | High | High | Very high
Allaire, 2020^80^ | Low | Low | Low | Some concerns | Low | Low | Some concerns | Some concerns
Andre, 2020^82^ | High | Some concerns | Low | Low | Low | Low | Low | Some concerns
Angulo, 2021^83^ | Some concerns | Low | Some concerns | Low | Some concerns | High | Some concerns | High
Arabshahi, 2017^84^ | High | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Baldwin, 2020^86^ | High | Low | Low | Low | Very high | High | Low | High
Baratali, 2021^87^ | Low | Low | Some concerns | Low | High | Low | High | High
Beslay, 2020^88^ | Low | Low | Some concerns | Low | Some concerns | High | Low | High
Best 2023^89^ | Low | Low | Low | Low | Some concerns | High | Some concerns | High
Bouzas, 2020^91^ | High | Low | Low | Some concerns | High | Low | High | High
Bouzas, 2022^90^ | Some concerns | Some concerns | Some concerns | Some concerns | Some concerns | High | Some concerns | High
Brayner, 2021^92^ | Low | Low | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Canhada, 2019^97^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Low | Some concerns
Canhada, 2022^96^ | Low | High | Some concerns | Low | Some concerns | Low | High | High
Cespedes Feliciano, 2016^99^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Chaltiel, 2019^100^ | Low | Low | Low | Low | Low | Some concerns | Some concerns | Some concerns
Chen, 2019 ^101^ | High | Some concerns | Some concerns | Low | Some concerns | Some concerns | High | High
Choi, 2020^102^ | High | Low | Low | Low | High | Low | Some concerns | High
Cordova, 2021^103^ | Low | Some concerns | Some concerns | Low | Some concerns | Very high | Some concerns | High
Cuenca-Garcia, 2014^105^ | High | Some concerns | Some concerns | Low | High | Low | Some concerns | High
Ericson, 2019^107^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns | High
Ford, 2017^109^ | Low | Some concerns | Low | Low | Some concerns | High | High | High
Fung, 2015^111^ | High | Some concerns | Some concerns | Low | Some concerns | High | Some concerns | High
Fung, 2021^110^ | High | Low | Low | Low | Low | High | Low | High
Funtikova, 2014^112^ | Low | Low | Low | Low | Some concerns | Low | Low | Some concerns
Glenn, 2021^116^ | Some concerns | Low | Low | High | Low | Low | High | High
Gomez-Donoso, 2018^117^ | Some concerns | Low | Some concerns | Low | Some concerns | High | Low | High
Gomez-Donoso, 2019^118^ | Some concerns | Low | Low | Low | Some concerns | High | High | High
Gomez-Donoso, 2019^119^ | Some concerns | Low | Some concerns | Low | Some concerns | High | High | High
Hennein, 2019^121^ | High | Low | Low | Low | Low | Some concerns | Some concerns | High
Hodge, 2021^122^ | Low | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Huo 2023^123^ | High | Some concerns | Low | Low | Low | High | Some concerns | High
Jennings, 2020^125^ | High | Low | Low | Low | High | Low | Some concerns | High
Johns, 2015^126^ | Very high | Low | High | High | Some concerns | Low | Some concerns | Very high
Jung, 2022^127^ | Low | Low | Some concerns | Low | Some concerns | Low | High | High
Kanerva, 2018^128^ | Low | Low | Low | Low | Some concerns | High | Some concerns | High
Kang, 2021^129^ | Low | Low | Low | Low | High | High | High | High
Khoury, 2022^130^ | Low | Low | Some concerns | Some concerns | Some concerns | Low | Some concerns | High
Kim, 2020^131^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Konieczna, 2019^133^ | Low | Low | Some concerns | Some concerns | Some concerns | Low | High | High
Konieczna, 2021 UP^132^ | Low | Some concerns | Some concerns | Some concerns | Some concerns | Low | Some concerns | High
Li, 2015^134^ | Low | Low | Low | Low | Low | Very high | Some concerns | Very high
Li, 2016^135^ | Some concerns | Low | Some concerns | Low | High | Low | Some concerns | High
Li, 20 UP^136^ | High | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | High
Li, 2022^137^ | Some concerns | Low | Low | Low | Low | Some concerns | Low | Some concerns
Lim, 2021^138^ | Low | Low | Some concerns | Low | High | Low | High | High
Liu, 2022^140^ | Low | Low | Some concerns | Low | Some concerns | Low | Low | Some concerns
Liu, 2023^141^ | Low | Low | Some concerns | Low | Some concerns | Low | High | High
Livingstone, 2022^143^ | Low | Low | Some concerns | Low | Very high | Low | High | Very high
Livingstone, 2022^142^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Maskarinec, 2017^147^ | Low | Low | Low | Low | Some concerns | Low | Some concerns | Some concerns
Maskarinec, 2020^146^ | Very high | Low | Low | Low | Some concerns | Low | Some concerns | Very high
Mattei, 2017^148^ | Low | Low | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Mendonca, 2016^149^ | Some concerns | High | Some concerns | Low | Low | Very high | Some concerns | Very high
Mirmiran, 2015^152^ | Some concerns | Some concerns | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns
Mirmiran, 2017^151^ | Some concerns | Low | Some concerns | Low | Some concerns | Low | Some concerns | High
Mirmiran, 2023^150^ | High | High | Some concerns | Low | High | Low | Some concerns | High
Olstad, 2017^154^ | Low | Low | Low | Low | Low | Very high | Low | Very high
Otto, 2015^155^ | High | Low | Low | Low | Some concerns | Low | Low | High
Perala, 2017^158^ | Low | Low | Low | Low | Low | Low | Low | Low
Pribisalić, 2021^160^ | Low | Low | Some concerns | Low | High | Some concerns | High | High
Rauber, 2021^161^ | Some concerns | Some concerns | Low | Low | High | Low | Some concerns | High
Riboldi, 2022^163^ | Low | Low | High | Low | High | Low | Some concerns | High
Roswall, 2014^164^ | Low | Low | Low | Low | Low | High | Some concerns | High
Rudakoff, 2022^165^ | High | High | Some concerns | Low | Some concerns | Low | Some concerns | High
San-Cristobal^166^ | High | Low | Low | High | Low | High | Low | High
Satija, 2019^167^ | Low | Low | Some concerns | Low | Some concerns | High | Some concerns | High
Shakeri, 2019^168^ | Some concerns | Low | Low | Low | Low | Low | Some concerns | Some concerns
Steffen, 2014^170^ | High | Low | Low | Low | Low | Low | Some concerns | High
Sweetman, 2023^171^ | High | Low | Some concerns | Low | Some concerns | Low | High | High
Tabung, 2019^172^ | Some concerns | Low | Some concerns | Low | Some concerns | Some concerns | Some concerns | High
Tobias, 2016^173^ | Some concerns | Low | Low | Low | Low | High | Some concerns | High
Um, 2023^176^ | Low | Some concerns | Low | Low | Low | High | Some concerns | High
Vinke, 2020^178^ | Some concerns | Low | Some concerns | Low | Some concerns | High | Low | High
Wang, 2018^179^ | Some concerns | Low | Low | Low | Low | High | Low | High
Winkvist, 2017^180^ | Some concerns | Low | Low | Low | Low | Low | Low | Some concerns
Xu, 2021^181^ | High | Some concerns | Low | Low | Some concerns | High | Some concerns | High
Yang, 2022^182^ | Low | Low | Some concerns | High | Low | High | High | High

## Dietary patterns during pregnancy

Twenty-five articles met the inclusion criteria examining the relationship between dietary patterns consumed during pregnancy and adequacy of total gestational weight gain (GWG). The included articles were published between January 2000 and May 2023 and came from three randomized controlled trials,^183–185^ 20 prospective cohort studies (21 articles) ^186–205^ and one retrospective cohort study.^206^ Two articles came from the MISC study in UAE, and the rest of the articles were from independent cohort studies.

### Description of the evidence

#### Population

Sample sizes of the studies ranged from N=114^198^ to N=56,529^186^ participants. Most participants were between 18 and 35 years old, with one study including adolescent participants (16 to 20 years).^206^

Five studies were conducted in the U.S.^185,187,195,196,203^ In addition, four studies were conducted in China,^190,194,197,204^ three were conducted in Spain,^183,198,206^ two in Norway^186,193^ and one study each in Canada,^202^ Iran,^199^ Mexico,^191^ Australia,^184^ Iceland,^189^ Malaysia,^192^ Brazil,^205^ Sweden,^212^ the UAE,^200,201^ and the Netherlands.^188^

##### Health status

Studies in this body of evidence included individuals during pregnancy who were representative of the general population, including those with overweight and obesity. Van Horn et al.,^185^ exclusively enrolled participants with overweight or obesity. Some articles noted that the mean pre-pregnancy BMI of the participants was between ~25 and ~28 kg/m^2^, ^191,195,196,199,201,203^ while Itani et al.,^201^ reported that ~60% of the participants had pre-pregnancy BMI ≥25 kg/m^2^ and Ancira-Moreno et al.^191^ noted that nearly half of the participants had overweight or obesity. Most articles reported that mean pre-pregnancy BMI ranged from 18.5 up to 25 kg/m^2^. ^183,184,186–190,192–194,197,198,202,204–206,212^

Many studies excluded participants with diabetes mellitus (type 1 or type 2) at baseline. However, some studies reported up to 20% of participants had gestational diabetes mellitus (GDM) in the current pregnancy.^189,200,201^ In studies that reported hypertensive disorders of pregnancy, the prevalence was <6%.^184,187,188,193,202^ A few studies excluded participants with incident hypertensive disorders of pregnancy^191^ and/or GDM.^183,191^

##### Race and/or ethnicity

About two-thirds of the articles reported race and/or ethnicity of the participants. Of these, 10 articles noted that ≥50% of the participants were White.^183–185,187,188,193,196,202,203,206^ Two articles reported that all of their participants were Hispanic and/or Latina^196,206^ and three other articles reported that ~21–40% of the participants were Hispanic.^183,185,195^

Black participants were largely under-represented, with a few studies reporting ≤25% Black participants.^185,187,195,203^ Although most articles did not report the proportion of participants of Asian descent, a few reported ~24–32%^184,195^ Asian participants. The majority of the participants from studies conducted in China were of Han ethnicity.^194,204^ Two articles from the same cohort in UAE reported that more than half of the participants were of Arab nationality.^200,201^

Several articles did not report race and/or ethnicity of the participants,^186,189,191,197–199^ and a number of articles only reported the percentage of participants who were White or "other.”^188,193,202^ No studies explicitly reported any American Indian or Alaskan Native participants, and it was not clear whether Native Hawaiians or Other Pacific Islanders were included.

##### Socioeconomic position

Education: In studies that reported education status, ≥50% of the participants had some university education or higher.^183,185,187,189,190,195,197,198,202,203,205^ Hillesund et al., 2018 did not report education level of the participants.^193^ One study reported that the majority of participants had “middle” to “high” education.^188^ About ~14% of the participants from a cohort in Mexico191 had ≥8 years of schooling and most participants from a Spanish study had lower or intermediate education.^206^ An Iranian study noted that <6% of the participants had a university degree.^199^

Income and/or Occupation: One-third of articles did not report participant income or occupation data, or the data was not easily interpretable.^186,189,191,196,198,203–206^ Of the studies that reported occupation data, a few noted that the majority of the participants were unemployed,^196,199,200^ while others reported that the majority of the participants were employed.^183,192,193^ One trial in Australia noted that ~17% of the participants were classified as most disadvantaged based on the Socio-economic Index for Areas—Index of Relative Socio-economic Disadvantage.^184^

##### Smoking

A majority of the articles reported smoking status of the participants, with some exceptions.^191,192,196,200,206^ A few studies excluded participants who smoked or reported that none of the participants smoked.^185,198,199^ Generally, studies stated <10% of the participants smoked (daily or occasionally) before or during pregnancy.^183,184,186,193,194,197,202,204^ ^205,212^ ^203^Notable exceptions were three articles that reported 16–30% of participants smoked before or during pregnancy.^188–190^

Most studies did not report data on alcohol consumption during pregnancy. However, 3 studies (including one conducted in the U.S.) reported that ~19%-47% of participants consumed alcohol during pregnancy.^188,203^ ^205^

#### Intervention/exposures

Dietary patterns were assessed using 1) index/score analysis, 2) factor/cluster analysis, 3) experimental diet, and 4) reduced rank regression. A description of the studies categorized by the method used to measure dietary patterns is included below and in. Sixteen articles included in this review used one or more of the following indices/scores summarized below:

- Healthy Eating Index (HEI) and its modifications ^187,195,196^
- Country-specific patterns ^186,188,191–193,197^
- Mediterranean Diet ^195,198,200,206^
- Dietary Approaches to Stop Hypertension (DASH)^195^
- Dietary risk scores^189^
- Maternal Diet Quality Score (MDQS)^191^
- Nova203
- Plant-based diet score (healthy, unhealthy)^199^
- Dietary quality index^212^
- Empirical Dietary Inflammatory Index^195^

Seven articles assessed dietary patterns using factor/cluster analysis.^188,190,196,201,202,204^ ^194^Three articles in this review assigned participants to an experimental diet (i.e., Mediterranean diet, DASH, HEI) or a control.^183–185^ Alves-Santos et al.,^205^ assessed adherence to dietary patterns derived using reduced rank regression.

#### Outcome

Studies that assessed adequacy of total GWG (i.e., in relation to recommendations based on pre-pregnancy BMI) were included in this body of evidence. Studies that examined GWG only during certain time periods or trimesters of pregnancy, or that examined absolute total GWG not in relation to recommendations based on pre-pregnancy BMI, were excluded.

Most studies classified GWG as inadequate, adequate, or excessive according to the Institute of Medicine (2009) guidelines^*^, with a few exceptions; Rifas-Shiman et al^187^ and Jayedi et al.^199^ used the Institute of Medicine (1990) guidelines,^†^ Hrolfsdottir et al^189^ used Icelandic recommendations (no reference provided), and Assaf-Balut et al^183^ cited a previous publication.^‡^

* Institute of Medicine (US) and National Research Council (US) Committee to Reexamine IOM Pregnancy Weight Guidelines. Weight Gain During Pregnancy: Reexamining the Guidelines. (Rasmussen KM, Yaktine AL, eds.). Washington (DC): National Academies Press (US); 2009

† Institute of Medicine (US) Committee on Nutritional Status During Pregnancy and Lactation. Nutrition During Pregnancy: Part I Weight Gain. Washington (DC): National Academies Press (US); 1990

‡ Hutcheon JA, Platt RW, Abrams B, Himes KP, Simhan HN, Bodnar LM. Pregnancy weight gain charts for obese and overweight women. Obesity. 2015; 23(3): 532–535. doi: 10.1002/oby.21011.25707378

### Synthesis of the evidence for excessive gestational weight gain

Twenty-two articles from three RCT, 18 articles from 17 prospective cohort studies and one RCS were considered in the evidence synthesis.(Table 21) Three cohort studies were not considered in the synthesis because of very high risk of bias, primarily due to critical issues with exposure measurement or missing data. ^204,212,205^

One trial^185^ and nine prospective cohort articles^186,191,193–195,197,200,201^ showed that at least one dietary pattern examined was associated with a decreased risk of excessive GWG and/or GWG rate (GWGR). Several studies also showed that greater alignment to an unhealthy dietary pattern (e.g., Western dietary pattern; ultra-processed food; margarine, sugar and snacks pattern) was associated with greater risk of excessive GWG.^188–190,201,203^ Eight studies examined dietary patterns using an index/score^186,189,191,193,195,197,200,203^ and four studies used factor/cluster analysis.^188,190,194,201^ Most of these dietary patterns shared the following positive components in common: fruits, vegetables, whole grains, legumes, nuts, dairy and fish; and one negative component in common: added sugar.

- Some studies specified dairy as a positive or negative component based on fat content (e0.g., low-fat dairy, skim milk, and reduced fat milk as a positive component; high-fat dairy a negative component) or the amount of intake (e.g., 2 to 5 times/day as positive component, >5 times a day as negative component); however, this was not consistent across studies.
- Except for five studies^187,191,192,197,198^ that assessed diet at least two times during pregnancy, most studies had a single dietary measurement at baseline.
- One cohort study showed that the modified Healthy Eating Index for Malaysians was associated with a greater risk of excessive GWG, which was inconsistent with results from other studies.^192^
- Studies also reported null findings or no significant association between dietary patterns consumed and excessive GWG or GWGR. Two trials^^183,184^^ showed no effect on excessive GWG; however, one of the trials had numerous methodological issues and hence was weighed less during the synthesis process.^183^ Several other cohort studies reported that some or all of the dietary patterns included did not show an association with excessive GWG or GWGR.^187–190,194–196,198–202,206^

Table 18 List of dietary patterns consumed during pregnancy that were examined in relation to gestational weight gain^*^ * Author-derived dietary patterns

Reference | Dietary pattern | Dietary components
Index/Score Analysis
Acosta-Manzano^198^ | Mediterranean Diet Score Index | Fruits; vegetables; fish (positive); Red meat/subproducts (negative); Whole-grain cereals; potatoes; pulses; olive oil; poultry; dairy products (unclear); Alcohol component excluded
Ancira-Moreno et al^191^ | Maternal Diet Quality Score | Vegetables and fruits; legumes; low-fat dairy products; PUFAs (positive); Red meat; added sugars; foods high in saturated fat or added sugar (negative)
Augustin et al^212^ | Dietary quality index | Fruit, vegetables, whole grain bread, fish, use of low-fat margarine (≤40%) (positive); Cheese, sausage, discretionary foods, use of high fat margarine or butter (≥60%) (negative)
Berube et al^196^ | Healthy Eating Index (HEI)-2015 | Total fruits, whole fruits, total vegetables, greens and beans, whole grains, dairy, total protein, seafood and plant protein, and fatty acids (positive); Refined grains, sodium, saturated fat, and added sugars (negative)
Cummings et al^203^ | Nova | “Instant” foods; ready-to-heat pre-prepared pies, pasta, and pizza dishes; mass-produced packaged breads; reconstituted meats; sweet or savory packaged snacks; confectionery desserts; sweetened drinks
Hillesund et al 2014^186^ | New Nordic Diet (NND) | Root vegetables; cabbages; potatoes relative to rice and pasta; Nordic fruits; foods from the wild countryside (game, fish, seafood, and native berries); whole grain breads relative to refined breads; oatmeal porridge; unsweetened milk relative to fruit juice; water relative to sweetened beverages; meal frequency (positive)
Hillesund et al 2018^193^ | Norwegian Fit for Delivery | Vegetables with dinner; fruits or vegetables as snacks; water relative to other beverages; small portion size of one or more unhealthy food items (soda, salty crisps, or chocolate); meal frequency; never eating sweets and snacks without appreciation; reading nutrition labels (positive); Sugar-rich food items; fast-foods, snacks, or other salty food; eating beyond satiety (negative)
Hrolfsdottir et al^189^ | Dietary risk score (13 risk factors) | Low intake of vegetables and fruits; whole grains; beans, nuts, and seeds; dairy; fish; vitamin D; Low dietary variety; High intake of processed meat; french fries and fried potatoes; dairy; sweets, ice cream, cakes, and cookies; sugar and artificially sweetened beverages; butter relative to oil
| Dietary risk score (6 risk factors) | Low intake of vegetables and fruits; whole grains; dairy; Low dietary variety; High intake of dairy; sugar and artificially sweetened beverages
| Dietary risk score (3 risk factors) | Low intake of whole grains; dairy; High intake of dairy; sugar and artificially sweetened beverages
Jayedi^199^ | Plant-based diet score | Healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); less healthy plant-based foods (fruit juices, refined grains, potatoes, sugar-sweetened beverages, sweets/desserts) (positive); Animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods) (negative)
| Healthy plant-based diet score | Healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee) (positive); Less healthy plant-based foods (fruit juices, refined grains, potatoes, sugar-sweetened beverages, sweets/desserts); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods) (negative)
| Unhealthy plant-based diet score | Less healthy plant-based foods (fruit juices, refined grains, potatoes, sugar-sweetened beverages, sweets/desserts) (positive); Healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods) (negative)
Liu et al^195^ | Healthy Eating Index (HEI)-2010 | Total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids (positive); Refined grains, sodium, and empty calories (negative); Alcohol excluded from empty calories component
| Dietary Approaches to Stop Hypertension (DASH) | Fruits, vegetables, nuts and legumes, low-fat dairy products, whole grains (positive); Sodium, red and processed meats, and sweetened beverages (negative); !!
| Alternate Mediterranean Diet (aMed) | Fish, whole grains, legumes, nuts, fruits, vegetables, and monounsaturated to saturated fat ratios (positive); Red and processed meat (negative); Alcohol component excluded
| Empirical Dietary Inflammatory Index (EDIP) | Tea, coffee, dark yellow vegetables, leafy green vegetables, snacks, fruit juice, pizza (positive); Processed meat, red meat, organ meat, other fish, other vegetables, refined grains, high-energy beverages, low-energy beverages, and tomatoes (negative); Alcohol component excluded
Radwan et al^200^ | alternative Mediterranean diet | Vegetables (not potatoes); legumes; fruit; nuts; whole grains; fish; MUFA/SFA (positive); Red and processed meat (negative); Alcohol component excluded
| Lebanese Mediterranean Diet | Whole grains/bulgur; olive oil; fruits; dried fruits; vegetables; starchy vegetables; legumes; eggs, dairy (positive)
Rifas-Shiman et al^187^ | Alternative Healthy Eating Index for Pregnancy (AHEI-P) | Vegetables (includes tofu and soybeans); fruits; ratio of white (poultry, fish) to red meat (beef, pork, lamb, processed); ratio of PUFAs to SFAs; fiber; calcium; folate; iron (positive); Trans fats (negative); Alcohol and nut components excluded
Silva-del-Valle et al^206^ | Mediterranean Diet | Olive oil as principal fat; olive oil servings; vegetables; fruit; pulses; fish, seafood; nuts; chicken, turkey, or rabbit in place of red meat or sausages; sofrito; wine (positive); Red meat/sausages; butter, margarine, cream; carbonated and/or sugar-sweetened beverages; commercial pastries (negative)
Tielemans et al^188^ | Dutch Healthy Diet Index | Vegetables; fruits; fish; fiber (positive); SFAs; sodium (negative); Alcohol, acidic food and drink, and trans fat components excluded
Yang et al^197^ | Chinese Healthy Diet Index for pregnancy | Grains, tubers and mixed beans; vegetables and fruits; meat, poultry, fish and eggs; dairy, soybeans and nuts (positive)
Yong et al192 | Modified Healthy Eating Index (HEI) for Malaysians | Vegetables; fruits; cereals and grains; legumes; poultry, meat, and eggs; fish and seafood; milk and milk products; total fats; sodium (negative)
Factor/Cluster Analysis *; * A posteriori dietary pattern
Hu et al^204^ | ‘Traditional’ | High intakes of tubers, vegetables, fruits, red meat, rice
| ‘Sweet foods’ | High intakes of sweet beverages, pastry and candy, shrimps, crabs and mussels, fruits
| ‘High protein’ | Fried foods, beans and bean products, dairy products and fruits
| ‘Milk-nut-seafood’ | High intakes of milk, nuts, shrimps, crabs and mussels, fruits, dairy products, eggs and egg products, pastry and candy and lower intake of sweet beverages
Jarman et al^202^ | ‘Tea and coffee’ pattern | Characterized by more frequent intakes of coffee, tea (both regular and decaffeinated), reduced-fat milk, full-fat milk, cream and added sugar
Li et al^194^ | ‘Beans-vegetables’ | Root vegetables, mushrooms and algae, melon and solanaceous vegetables, Beans and bean products (soybean, mung bean, soybean milk, bean curd, etc), Leafy and cruciferous vegetables
| ‘Fish-meat-eggs’ | Red meat, freshwater fishes, eggs
| ‘Nuts-whole grains’ | Nuts, whole grains, dairy products
| ‘Organ-poultry-seafood’ | Animal organ and blood, seafood, poultry
| ‘Rice-wheat-fruits’ | Rice and wheat products, fruits
Itani et al^201^ | ‘Diverse’ | Consumption of fruits, vegetables, mixed dishes, meats, dairy, grains, legumes and nuts, fats and oils
| ‘Western’ | High intakes of sweets, sweetened beverages, added sugars, fast food, eggs, offals
Tielemans et al^188^ | ‘Vegetable, Oil and Fish’ | High intake of vegetables, oil, and fish
| ‘Nuts, High-Fiber Cereals, and Soy’ | High intake of nuts, high-fiber cereals, and soy
| ‘Margarine, Sugar, and Snacks’ | High intake of margarine, sugar, and snacks
Wei et al^190^ | ‘Cereals’ | Richer in cereals
| ‘Vegetables’ | Richer in vegetables
| ‘Meats’ | Richer in meats
| ‘Fruits’ | Richer in fruits
| ‘Fish, beans, nuts, and yogurt’ | Richer in fish, beans, nuts, and yogurt
| ‘Milk and milk powder’ | Richer in milk and milk powder
Experimental Diet
Assaf-Balut et al^183^ | Control | Mediterranean Diet: High consumption of vegetables, fruit (avoiding juices), skimmed dairy products, whole grain cereals, and legumes; moderate-to-high consumption of fish; low consumption of red and processed meat; avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods, and precooked meals; restriction of dietary fat, including extra virgin olive oil (EVOO) and nuts
| Intervention | Mediterranean Diet plus EVOO and pistachios provided by investigators
Dodd et al^184^ | Lifestyle advice | Dietary advice consistent with Australian dietary standards, participants were advised to increase their intake of fiber, and to consume two servings of fruit, five servings of vegetables and three servings of dairy each day
| Standard care | Received antenatal care according to hospital guidelines (did not include information relating to dietary intake)
Van Horn et al^185^ | Mama-Dietary Approaches to Stop Hypertension (DASH) | Encouraged consumption of low-fat dairy products, fish, skinless poultry, lean meat and vegetable protein, unsaturated fats, fiber-rich whole grains, fruits, vegetables, and legumes; discouraged consumption of sugar-sweetened beverages, sweets, and non-nutrient-dense snack foods; avoidance of fish considered higher in mercury; inclusion of calcium-rich, vitamin D–enriched dairy, or calcium-fortified non-dairy products
| Control | Usual care, including bi-weekly newsletters and publicly available maternity website links
Alves Santos et al^205^ | Common-Brazilian | Higher in beans; rice; lower in fast food and snacks; candies and table sugar; processed meats and bacon
Alves Santos et al^205^
Alves Santos et al^205^ | Western | Higher in fast food and snacks; processed meat and bacon. Lower in noodles, pasta, roots, and tubers; sodas

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?” based on their review of the body of evidence examining dietary patterns consumed during pregnancy and excessive gestational weight gain. (Table 19)

Table 19 Conclusion statement, grades for dietary patterns consumed during pregnancy and excessive gestational weight gain*

Conclusion Statement | Limited evidence suggests that dietary patterns consumed during pregnancy may be associated with a lower risk of excessive gestational weight gain. These patterns tend to emphasize higher intakes of fruits, vegetables, whole grains, legumes, nuts, dairy and fish and lower intakes of added sugar.
Grade | Limited
Body of Evidence | 22 articles: 3 RCT, 18 prospective cohort studies, 1 RCS
Consistency | Serious issues with consistency across trials, partially explained by participant pre-pregnancy BMI. Heterogeneity in the dietary patterns across cohort studies. Yet, many showed favorable associations, with statistically non-significant findings pointing to favorable association.
Precision | Serious issues with precision, with few trials reporting power analyses for GWG outcomes. Despite adequate power and sample size, cohort studies reported results with wide confidence intervals and values close to null.
Risk of bias | Serious issues with trials generally having high risk of bias, with concerns about deviations from intended interventions and selection of reported results. Most cohort studies had high or serious risk of bias because of confounding, missing data, and selection of reported results.
Directness | Serious issues with directness, with only one trial designed to address the effect of dietary patterns on GWG. The intervention in another trial focused only on certain foods and did not fully align with the intervention/exposure in the analytic framework. Despite most observational studies having GWG as the primary outcome, substantial issues were noted as the definitions of dietary patterns were not consistent and GWG was measured at different time points.
Generalizability | Serious issues, with only one trial conducted in the U.S. Across trials and cohort, the participants did not fully reflect the diversity of the U.S. population.

#### Assessment of evidence for excessive GWG

This body of evidence included both large and small studies with significant as well as null findings, so publication bias may have been less likely. As outlined and described below, the body of evidence was assessed for the following elements used when grading the strength of evidence.

##### Consistency

Of the three trials, only Van Horn et al.,^185^ showed a beneficial effect of the dietary pattern on excessive GWG. Dodd et al.,^184^ reported findings that approached statistical significance and Assaf-Balut et al.,^183^ did not show a statistically significant effect. The heterogeneity in findings may be due to the underlying differences in the population’s pre-pregnancy BMI or health status. Van Horn et al.^185^ exclusively enrolled participants with overweight or obesity; whereas Dodd et al.,^184^ enrolled participants with BMI 18.5–24.9 kg/m^2^. Assaf-Balut et al.,^183^ restricted participants to those who were normoglycemic. Across cohort studies, there was heterogeneity in the dietary patterns and in the foods and food groups that each pattern included. Despite the heterogeneity, a good number of studies showed beneficial associations and most of the other studies reported non-significant results that tended to be in the same direction as statistically significant results.

##### Precision

The body of evidence included only three RCT, although they had reasonable sample sizes of 280 to 697 participants. Many studies reported power calculations; yet most of them were not for the outcome of interest (i.e., GWG). Although most cohort studies had adequate power and sample size, the results were generally statistically non-significant with wide confidence intervals and had small magnitudes.

##### Risk of bias

The overall risk of bias for RCT was high for two trials and low for one, Table 22. The concerns in these trials regarded deviations from intended interventions due to issues with adherence and selection of reported results, primarily due to not reporting the analysis plan a priori. Most observational studies had high or serious risk of bias (Table 23, Table 24). This was primarily driven by issues with confounding, missing data, and selection of reported results. None of the cohort studies adjusted for all the key confounders. Similar to the trials, most of the cohort studies did not report an a priori analysis plan.

##### Directness

Only one trial was designed to test the effect of dietary patterns on GWG.^185^ Further, the intervention in another trial^183^ focused only on certain foods and did not fully align with the intervention/exposure in the analytic framework. With regard to cohort studies, although most of the articles included in the body of evidence were designed to assess the effect of dietary patterns on GWG, definitions of dietary patterns were not consistent and not all foods included in the conclusion statement were included in all the dietary patterns. There was also heterogeneity in outcome measurement, with studies assessing GWG at different timepoints during pregnancy.

##### Generalizability

Only one trial included U.S. participants^185^ and the other trials did not reflect the diversity of the U.S. population. Although many cohort studies included non-U.S. populations (e.g., Malaysian, Chinese, Lebanese, Nordic), they did not fully reflect the diversity of the U.S. population either. Further, some of the dietary patterns in these studies were not reflective of U.S. diets.

### Synthesis of the evidence for inadequate gestational weight gain

Eighteen articles, including two RCT, 15 articles from 14 prospective cohort studies and one RCS were considered in the evidence synthesis. Augustin et al.,^212^ a Swedish cohort study was not considered during synthesis because of very high risk of bias due to issues with exposure measurement.

Eight cohort studies showed that at least one dietary pattern examined was associated with a decreased risk of inadequate GWG and/or GWGR.^186,190–192,194,199–201^ Of these, five articles assessed dietary patterns using index score analysis and three articles used factor/cluster analysis.

Many studies that examined dietary patterns did not find an association with inadequate GWG or GWGR. Both trials^183,184^ showed no effect on inadequate GWG, one of which had numerous methodological issues and hence was weighed less during the synthesis process.^183^ Several cohort studies reported that at least one or all of the patterns included did not show an association with inadequate GWG or GWGR.^187,188,190,193,195–197,199–201,203^ Two dietary patterns (beans-vegetables and Med Diet) showed at least one detrimental association with inadequate GWG.^194,206^

Overall, only a few cohort studies showed a significant association between dietary patterns and inadequate GWG, which were not consistent in the composition of dietary patterns or in the direction of results. Further, no RCT showed an effect of dietary patterns on inadequate GWG. The lack of association could be due to methodological limitations, as noted by high risk of bias for most of the studies, or differences in pre-pregnancy BMI. One RCT had a high risk of bias due to deviation from intended intervention and selection of reported results (Table 22). In addition, many observational studies had issues with confounding and missing data (Table 23, Table 24). This body of evidence included both large and small studies with significant as well as null findings, so publication bias may have been less likely.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?” based on their review of the body of evidence examining dietary patterns consumed during pregnancy and inadequate gestational weight gain. (Table 20).

Table 20 Conclusion statement, grades for dietary patterns consumed during pregnancy and inadequate gestational weight gain

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of inadequate gestational weight gain because there are substantial concerns with consistency in the body of evidence.
Grade | Grade not assignable
Body of Evidence | 18 articles: 2 RCT, 15 prospective cohort studies, 1 RCS
Rationale | The available evidence was too inconsistent to draw conclusions on the relationship between dietary patterns and inadequate gestational weight gain.

Table 21 Evidence examining the relationship between dietary patterns consumed during pregnancy and gestational weight gain^a^

Study Characteristics | Intervention or Exposure and Outcome | Results | Confounding and Funding
RCT
Assaf-Balut, 2019 ^183^; RCT, Spain, St. Carlos GDM Prevention Study; Baseline N=1000; Analytic N=697 (Attrition: 30%); - Age: ∼33.0y; - Race/Ethnicity (%):; ○ White: 67.5; Hispanic: 29.7; Other: 2.8; - Socioeconomic position:; ○ Education (%): University degree: 50.8; ○ Employed (%): 77.3; - Pre-pregnancy BMI: 22.6; - Smoking (%): 7.9; - DM/HDP (%):; ○ GDM: 0.0; ○ Gestational HTN: CG: 3.3; IG: 3.6; ○ PE: CG: 1.2; IG: 1.9 | IG vs. CG; FFQ at: 8–12 GW, 24–28 GW, and 36–38 GW; DP Descriptions:; - Both the intervention group (IG) and control group (CG) given the same basic MedDiet recommendations: ≥2 servings/d vegetables, ≥3 servings/d fruit (avoiding juices), 3 servings/d skimmed dairy products, wholegrain cereals, 2–3 servings legumes/wk, moderate to high consumption of fish; low consumption of red and processed meat, avoidance of refined grains, processed baked goods, pre-sliced bread, soft drinks and fresh juices, fast foods and precooked meals. They were also instructed to be physically active and walk ≥30 min/d.; - IG recommended to consume ≥40 mL/d of EVOO and a handful (25–30 g/d) of pistachios and were provided with 10 L EVOO and 2 kg roasted pistachios at 12–14 GW and 24–28 GW.; - CG recommended to restrict dietary fat, including EVOO and nuts.; Adherence: MEDAS scores did not differ at baseline but were higher in IG at 24–28 GW and 36–38 GW. Physical activity scores did not differ at either follow-up point.; Outcome and assessment methods:; GWG assessed at: baseline (12–14 GW) to 36–38 GW. Weight measured by investigators.; GWG adequacy defined according to pre-pregnancy BMI: <25: 9 kg, 25–29: 6 kg, 30–34.9: 3 kg, and ≥35: 0 kg.; Weight gain 3 kg below designated target categorized as insufficient. Weight gain 3 kg above designated target categorized as excessive. | GWG Adequacy; Chi-squared test, %; Excessive: CG: 26.7; IG: 27.5; Adequate: CG: 70.9; IG: 69.2; Inadequate: CG: 2.4; IG: 3.3; p=0.713 | Limitations: Issues with deviation from intended intervention and selection of the reported results; Funding: Fundación para Estudios Endocrinometabolicos, IdISSC Hospital Clínico San Carlos; the Instituto de Salud Carlos III of Spain
Dodd, 2019 ^184^; RCT, Parallel-arm, Australia, OPTIMISE; Baseline N=641; Analytic N= 629 (Attrition: 1%); - Age (y): 31.53±4.76; - Race/Ethnicity (%): White: 67.46; Asian: 15.01; Indian, Pakistani, Sri Lankan: 8.06; Other: 9.47; - Socioeconomic position:; ○ SEIFA IRSD (%): Quintile 1 (most disadvantaged): 16.75; Quintile 5: 17.85; - Baseline BMI: Median (IQR): 22.20 (20.87, 23.60); - DM/HDP (%):; ○ T1 or T2 DM: 0.0; ○ GDM: LI: 12.43; SC: 12.46; ○ Gestational HTN: LI: 1.58; SC: 1.30; ○ PE/Eclampsia: LI: 1.90; SC: 2.91; - Smoking (%): 4.42 | LI vs. SC; FFQ at: trial entry (10–20 GW), 28 GW and 36 GW; DP Descriptions:; - Lifestyle Intervention (LI): Received 3 in-person visits and 3 phone calls with dietitian or research assistant at trial entry, and 20, 24, 28, 32, and 36 GW. Dietary advice was consistent with current Australian dietary standards, maintaining a balance of carbohydrates, fat, and protein, and encouraging reduced intake of energy dense and non-core foods high in refined carbohydrates and saturated fats. Participants were advised to increase their intake of fibre, and to consume 2 svg/d fruit, 5 svg/d vegetables and 3 svg/d dairy.; - Standard Care (SC): Received antenatal care according to hospital guidelines, which did not include information relating to dietary intake, physical activity or weight gain during pregnancy.; Adherence: HEI scores from FFQ did not differ at baseline,but were higher in LI at 28 GW and 36 GW. Physical activity scores did not differ at either follow-up.; Outcome and assessment methods:; GWG assessed at: trial entry (10–20 GW) to 36 GW Weight measured by investigators.; Average weekly gWg methods NR. GWG adequacy by 2009 IOM recommendations. | Total GWG Adequacy; Logistic regression; Incidence (%), Adj Estimate (95% CI), kg; Below: LI: 50.71; SC: 51.68, 0.85 (0.60, 1.21), p=0.37; Within: LI: 40.57; SC: 35.16, (Ref); Above: LI: 8.72; SC: 13.16, 0.58 (0.32, 1.04); p=0.07; Weekly GWG Adequacy; Logistic regression; Incidence (%), Adj Estimate (95% CI), kg; Below: LI: 19.25; SC: 14.78, 1.36 (0.82, 2.26); p=0.24; Within: LI: 33.12; SC: 35.47, (Ref); Above: LI: 47.63; SC: 49.75, 1.02 (0.70, 1.48); p=0.92 | Other covariates: History (family or self) of GDM or HDP; Limitations:; Funding: The University of Adelaide; Lloyd Cox Strategic Research Excellence Award; NHMRC Practitioner Fellowship
Van Horn, 2018 ^185^; RCT, United States, MOMFIT; Baseline N=281; Analytic N=280 (Attrition: 0%); - Age: ∼33.6y; ○ Race/Ethnicity (%): White: ∼63.3; Hispanic: ∼21.4; Black/African American: ∼19.2; Other: ∼17.4; - Socioeconomic position:; ○ Education (%): ≤High school/GED: ∼4.6; Postgraduate work: ∼40.2; ○ Total family income (%): <$20,000: ∼4.6; ≥$200,000: ∼17.4; - Pre-pregnancy BMI: ∼31; ○ (%): ≥30: ∼54.8; - Smoking (%): 0.0; - DM/HDP (%):; ○ T1 or T2 DM: 0.0; ○ GDM: ∼6.0 | Mama-DASH vs. UC; 24 hr recall at 15 GW and 36 GW; DP Descriptions:; - Mama-DASH: Encouraged: low-fat dairy, fish, skinless poultry, lean meat and vegetable protein, unsat fat, fiber-rich whole grains, fruits, vegetables, legumes; Discouraged SSB, sweets, non-nutrient-dense snack foods; Caloric restriction to meet GWG, following nutrition guidelines for pregnant women, including avoidance of fish considered higher in mercury, inclusion of calcium-rich, vitamin D–enriched dairy, or calcium-fortified non-dairy products; Individual and group diet & PA counseling sessions; - Usual Care (UC): Received usual-care, including biweekly newsletters and publicly available maternity website links via email; Adherence: DASH and HEI-2010 scores did not differ at baseline,but were higher in the Mama-DASH group at 35 GW. Physical activity scores did not differ at 35 GW.; Outcome and assessment methods:; GWG calculated as difference between self-reported pre-pregnancy weight and weight measured by blinded, trained staff at 35 GW (weight closest to this time extracted from clinic charts or taken from previous study visits if no 35 GW measure available). GWG adequcy determined by IOM 2009 recommendations. | Excessive GWG; [underlined: All participants:]; UC: 84.4%; Mama-DASH: 68.6%; p=0.004; [underlined: Pre-pregnancy BMI 25–29.9]; UC: 86%; Mama-DASH: 79%; p=0.33; [underlined: Pre-pregnancy BMI >30]; UC: 83%; Mama-DASH: 60%; p=0.001 | Limitations: Issues with deviation from intended intervention; Funding: NIDDK, NHLBI; NICHD; NCCIH; ORWH; OBSSR; the Indian Health Service
Cohort Studies
Index/Score
Acosta-Manzano, 2022 ^198^; PCS, Spain, GESTAFIT; Analytic N =114; - Age (y): 33±5; - Socioeconomic position:; ○ Education (%): Non-university level: 36.4; University degree: 63.6; - Pre-pregnancy BMI: 23.7±3.9; - DM/HDP (%):; ○ Cardiometabolic disruptions: 0.0; - Smoking: Cigarettes/d (Median (IQR)): 0 (0, 0) | Mediterranean Diet Score (continuous adherence); FFQ at: 16 GW, 33 GW; DP Description:; - Positive components: fruits; vegetables; fish; - Negative components: red meat/subproducts; - Unclear: whole-grain cereals; potatoes; pulses; olive oil; poultry; dairy products; Outcome and assessment methods:; Excessive GWG assessed at: Pre-pregnancy to 33 GW Body weight measured by investigators. GWG adequacy by 2009 IOM recommendations | Excessive Total GWG; Logistic regression; OR (95% CI): 0.92 (0.79, 1.07); β (SE), kg: −0.09 (0.08), p=0.26; TEI adjustment: p=0.41 | Key confounders accounted for: Age, Pre-pregnancy BMI, Smoking, DM in the current pregnancy, HDP in the current pregnancy; Key confounders not accounted for: Physical activity, Race and/or ethnicity, Socioeconomic position, Parity; Other covariates: In-bed time, sleep (duration, awakening time after onset, efficiency, quality), upper body muscle strength, cardiorespiratory fitness; Limitations: Issues with confounding, participant selection, and missing data; some concerns about post-exposure interventions and selection of reported results; Funding: University of Granada, the Spanish Ministry of Economy and Competitiveness, the Spanish Ministry of Education, Culture and Sports, Instituto de Salud Carlos III, European Social Fund
Ancira-Moreno, 2019 ^191^; PCS, Mexico, PRINCESA; Analytic N=660; - Age: ∼24.9y; - Socioeconomic position:; ○ >9y education: ∼14.2%; - Pre-pregnancy BMI: ∼25.7; - DM/HDP (%):; ○ GDM: 0.0; ○ PE: 0.0 | Maternal Diet Quality Score (tertiles of alignment); 24 hr recall at: each prenatal visit (∼every 5 GW); DP Description:; - Positive components: PUFA, fruits and vegatables, low fat dairy, legumes; - Negative components: Added sugars, red meat, foods high in saturated fat or added sugar; Outcome and assessment methods:; Weight measured at first and consecutive visits by trained staff using standardized methods. Pre-pregnancy weight self-reported. GWGR (kg/wk) calculated as weight at current visit minus weight from previous visit, divided by follow-up duration. First GWGR estimated using pre-pregnancy weight. GWGR adequacy based on 2009 IOM recommendations. | Inadequate GWGR; Mixed-effect logistic regression; OR (95% CI); [underlined: All participants]; T2 vs T1 (Ref): 0.74 (0.56, 0.99), p=0.044; T3 vs T1 (Ref): 0.63 (0.42, 0.95), p=0.031; [underlined: Pre-pregnancy BMI <25]; T2 vs. T1 (Ref): 0.43 (0.18, 0.99),p=0.046; T3 vs. T1 (Ref): 0.30 (0.09, 0.95),p=0.040; [underlined: Pre-pregnancy BMI ≥25]; T2 vs. T1 (Ref): 0.10 (0.01, 0.91),p=0.044; T3 vs. T1 (Ref):0.03 (0.002, 0.44), p=0.01; Excessive GWGR; Mixed-effect logistic regression; OR (95% CI); [underlined: All participants]; T2 vs. T1 (Ref): 0.77 (0.57, 1.04),p=0.094; T3 vs. T1 (Ref): 0.62 (0.41, 0.94),p=0.025; [underlined: Pre-pregnancy BMI <25]; T2 vs. T1 (Ref): 0.35 (0.13, 0.95),p=0.040; T3 vs. T1 (Ref): 0.24 (0.06, 0.99),p=0.048; [underlined: Pre-pregnancy BMI ≥25]; T2 vs. T1 (Ref): 0.08 (0.13, 0.92),p=0.042; T3 vs. T1 (Ref): 0.08 (0.06, 0.999),p=0.05 | Key confounders accounted for: Age, Physical activity, Socioeconomic position, Pre-pregnancy BMI, Parity, DM in the current pregnancy, HDP in the current pregnancy; Key confounders not accounted for: Race and/or ethnicity, Smoking; Other covariates: TEI, GA, Fetal sex, Marital status; Limitations: Issues with confounding, exposure measurement, participant selection, and selection of the reported results; some concerns about missing data, outcome measurement,; Funding: The Capital Semilla of the Division of Social Studies; Academic Vice Presidency of the Universidad Iberoamericana
Augustin, 2020 ^212^; PCS, Sweden, GraviD; Analytic N =1113; - Age (y): 31.9±4.6; - Socioeconomic position:; ○ Education (%): Primary: 1.5; Secondary: 29.8; University: 68.9; - BMI at first visit: 24.1±4.0; - Smoking (%): Tobacco use in early pregnancy: 3.9 | Dietary quality index (High vs. Fair and Poor); FFQ at: TM3; DP Description:; - Positive components: fruit, vegetables, whole grain bread, fish, use of low-fat margarine (≤40%); - Negative components: cheese, sausage, discretionary foods, use of high fat margarine or butter (≥60%); Outcome and assessment methods:; GWG assessed at: ≤14 GW to 37±2 GW; Body weight retrieved from medical records. GWG calculated as weight at 37±2 GW minus weight ≤14 GW. GWG adequacy by 2009 IOM recommendations. | Insufficient GWG; Logistic regression; OR; Fair vs High (Ref): 0.58, p=0.17; Poor vs High (Ref): 0.40, p=0.02; Adequate GWG; Logistic regression; OR; Fair vs High (Ref): 0.80, p=0.57; Poor vs High (Ref): 0.83, p=0.63; Excessive GWG; Logistic regression; OR; Fair vs High (Ref): 3.3, p=0.04; Poor vs High (Ref): 4.4, p=0.01 | Key confounders accounted for: Age, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity, DM in the current pregnancy, HDP in the current pregnancy; Key confounders not accounted for: Physical activity, Race and/or ethnicity; Other covariates: GA at the time of registration, gestational duration; Limitations: Issues with confounding, exposure measurement, and missing data; some concerns about participant selection and selection of the reported results; Funding: The Swedish Research Council for Health, Working Life and Welfare, grant number 2018–00441 and Regional Research and Development Grant
Berube, 2023 ^196^; PCS, United States, StEP; Analytic N =500; - Age (y): HEI-2015 T1: 27±6; HEI-2015 T3: 30±6, p<0.0001; - Race/Ethnicity (%): Hispanic/Latina: 100; - Socioeconomic position:; ○ Education (%): <High school: 33.6; ≥High school: 66.4; ○ Employed (%): 24.8; - Pre-pregnancy BMI: 27.5±5.5 | HEI-2015 (tertiles of adherence); FFQ at: At baseline (28–32 GW); DP Description:; - Positive components: total vegetables; greens and beans; total fruit; whole fruit; whole grains; seafood and plant proteins; total protein foods; dairy; PUFA+MUFA/SFA.; - Negative components: refined grains; added sugars; SFA; sodium; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; Pre-pregnancy weight (first measured weight at ≤12 GW) and weight at delivery were extracted from medical records. If the first measured weight taken at >12 GW, self-reported pre-pregnancy weight was used. GWG calculated by subtracting pre-pregnancy weight from weight at delivery. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Multinomial logistic regression; OR (95% CI); T1: Ref; T2: 1.1 (0.7, 1.9); T3: 1.0 (0.6, 1.8); Excessive GWG; Multinomial logistic regression; OR (95% CI); T1: Ref; T2: 0.8 (0.5, 1.5); T3: 0.9 (0.5, 16) | Key confounders accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Parity; Key confounders not accounted for: Smoking, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: TEI; Limitations: Issues with post-exposure interventions; some concerns about confounding, exposure measurement, participant selection, and selection of the reported results; Funding: USDA NIFA, NICHD, HRSA
Cummings, 2022 ^203^; PCS, United States, PEAS; Analytic N=367; - Age (y): 30.5±4.7; - Race/Ethnicity (%): White: 71; Black: 17, Asian: 5, Other or multiracial: 6; Hispanic: 9; - Socioeconomic position:; ○ Income-Poverty Ratio: 3.84±1.97; ○ Education (%): College degree: 72; - Pre-pregnancy BMI (%): <18.5: 0.0; ≥25: 25.1; >30: 27.1; - GWG (%): Inadequate: 19; Adequate: 34; Excessive: 47; Smoking (%): Current: 2; Former: 18 | Nova (continuous adherence, % energy intake z-scored); ASA24 at: Baseline (<12 GW), TM2 (16–22 GW), TM3 (28–32 GW); DP Description:; - Positive components: ‘instant’ foods; ready-to-heat pre-prepared pies, pasta, and pizza dishes; mass-produced packaged breads; reconstituted meats; sweet or savory packaged snacks; confectionery desserts; sweetened drinks; Outcome and assessment methods:; GWG assessed at: <12 GW, 35±0.75 GW; Calculated as differences between weight at baseline (<12 GW) and last prenatal visit. GWG adequacy by 2009 IOM recommendations.; Weight, height measured by investigators, and from prenatal medical records. | Excessive GWG; Logistic regression; OR (95% CI), Adequate (Ref); 1.31 (1.01, 1.70), p=0.045; Inadequate GWG; Logistic regression; OR (95% CI), Adequate (Ref); 0.88 (0.63, 1.23), p=0.451 | Key confounders accounted for: Age, Physical activity, Socioeconomic position, Pre-pregnancy BMI, Smoking,; Key confounders not accounted for: Race and/or ethnicity, Parity, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: TEI, time; Limitations: Issues with confounding; some concerns about exposure measurement, missing data, and selection of the reported results; Funding: NICHD, NIH
Hillesund, 2014 ^186^; PCS, Norway, MoBa; Analytic N=56629; - Age: 30.1±4.6y; - Socioeconomic position:; ○ Education (%): ≤12y: ∼33.3; ≥17y: ∼33.3; - Pre-pregnancy BMI: 24.0± 4.2; - Smoking (%): ∼7.2; - DM/HDP (%):; ○ DM: 0.0 | New Nordic Diet (tertiles of alignment); FFQ at: 22 GW; DP Description:; - Positive components: eating/drinking ≥24 main meals/wk; Nordic fruits; root vegetables; cabbage; potatoes ≥1/3 of total occasions of potatoes, rice, or pasta; whole grain bread; oatmeal; fish/game/berries; milk; water; - Negative components: Refined grains; fruit juice; SSB; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; Pre-pregnancy weight self-reported at 17 GW. Delivery weight self-reported at 6mo postpartum. GWG adequacy by 2009 IOM recommendations | Inadequate GWG; Multinomial logistic regression; OR (95% CI); [underlined: Pre-pregnancy BMI <25]; T2 vs. T1 (Ref): 0.99 (0.92, 1.07), p=NS; T3 vs. T1 (Ref): 0.98 (0.91, 1.06), p= NS; [underlined: Pre-pregnancy BMI ≥25]; T2 vs. T1 (Ref):0.86 (0.74, 0.99), p=0.038; T3 vs. T1 (Ref): 0.90 (0.77, 1.06), p=NS; Excessive GWG; Multinomial logistic regression; OR (95% CI); [underlined: Pre-pregnancy BMI <25]; T2 vs. T1 (Ref): 0.99 (0.93, 1.06), p=NS; T3 vs. T1 (Ref):0.93 (0.87, 0.99), p=0.024; [underlined: Pre-pregnancy BMI ≥25]; T2 vs. T1 (Ref): 1.01 (0.92, 1.14), p=NS; T3 vs. T1 (Ref): 1.11 (1.00, 1.23), p=NS | Key confounders accounted for: Age, Physical activity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity, DM in the current pregnancy; Key confounders not accounted for: Race and/or ethnicity, HDP in the current pregnancy; Other covariates: TEI, Length of gestation; Limitations: Issues with confounding, participant selection, outcome measurement, and selection of the reported results; some concerns about exposure measurement, deviations from intended interventions, and missing data; Funding: Norwegian Ministry of Health; Norwegian Ministry of Education and Research; NIEHS; NINDS; Norwegian Research Council/FUG; University of Agder
Hillesund, 2018 ^193^; PCS, Norway, NFFD; Analytic N=524; - Age: 28.0±4.4y (range 18–44y); ○ (%): ≥35y: 6.8; - Race/Ethnicity: “predominantly White, European”; - Socioeconomic position:; ○ Education (%): ≤12y: 31.8; ≥16y: 35.5; ○ Occupation (%): Outside home: 84.2; Student: 8.7; Unemployed: 3.9; Sick leave/disabled: 1.9; Homemaker: 1.4; ○ Income (%): ≤400,000 NOK: 31.2; >700,000 NOK: 34.4; NR: 6.6; - Pre-pregnancy BMI: 23.7± 3.9; ○ (%): 25–29.9: 20.2; ≥30: 7.6; - Smoking (%): 3.9; - DM/HDP (%):; ○ GDM: 9.1; ○ PE: 4.3; ○ Severe PE/HELLP/eclampsia: 2.6 | Norwegian Fit for Delivery (continuous alignment); FFQ at: 15 GW; DP Description:; - Positive components: eating/drinking ≥24 main meals/wk; water for ≥44% of drinking events, vegetables with dinner ≥5x/wk, fruits or vegetables as snacks ≥3x/wk, <1x/d sugar-rich food items, <1x/d fast-foods, snacks, or other salty food, never eating sweets and snacks without appreciation, buying small portion size of ≥1 unhealthy food items, eating beyond satiety <1/wk, and reading nutrition labels on foods sometimes or often.; - Negative components:; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to final measured weight within 2wk of delivery; Pre-pregnancy weight self-reported. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Multivariate logistic regression; OR (95% CI); [underlined: Main analysis]; 1.05 (0.94, 1.17), p=0.381; [underlined: Sensitivity analysis additionally adjusting for PA]; 1.02 (0.95, 1.19), p=0.374; Excessive GWG; Multivariate logistic regression; OR (95% CI); [underlined: Main analysis]; 0.90 (0.83, 0.99), p=0.024; [underlined: Sensitivity analysis additionally adjusting for PA]; 0.88 (0.79, 0.97), p=0.009 | Key confounders accounted for: Age, Physical activity (in sensitivity analysis), Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity, DM in the current pregnancy, HDP in the current pregnancy; Key confounders not accounted for: Race and/or ethnicity; Other covariates: Marital status, Original trial randomization assignment; Limitations: Issues with confounding, exposure measurement, missing data, and selection of the reported results; some concerns about participant selection, deviations from intended interventions, and outcome measurement; Funding: South-Eastern Norway Regional Health Authority; Municipalities of southern Norway; University of Agder
Hrolfsdottir, 2019 ^189^; PCS, Iceland, PREWICE; Analytic N=1326; - Age: 30.2± 5.2y; - Socioeconomic position:; ○ Education (%): Elementary: 13; High & technical school: 29; Higher academic: 24; - Pre-pregnancy BMI: 24.1± 6.5; ○ (%): 25.0–29.9: 24; ≥30: 18; - Smoking (%): Before pregnancy: 16; During pregnancy: 7; - DM/HDP (%):; ○ GDM: 19.9 | 3 dietary risk factors score, 6 dietary risk factors score, & 13 dietary risk factors score (continuous alignment, tertiles of alignment); FFQ at: 11–14 GW; DP Descriptions:; [underlined: 3 dietary risk factors score:]; - Positive components: Whole grains; - Negative components: SSB, dairy ≥5x/d; [underlined: 6 dietary risk factors score:]; - Positive components: Varied diet (eating all main food groups); vegetables and fruit; dairy (2-<5x/d); whole grains; - Negative components: SSB, dairy (<2 or ≥5x/d); [underlined: 13 dietary risk factors score:]; - Positive components: Varied diet (eating all main food groups); vegetables and fruit; fish; dairy (2-<5x/d), whole grains; beans, nuts, and seeds; vitamin D; - Negative components: French fries; sweets and desserts; SSB; processed meat; dairy (<2 or ≥5x/d); butter vs oil; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to highest recorded weight ≥36 GW; GWG retrieved from hospital records. Excessive GWG defined by Icelandic recommendations: >18 kg for participants with pre-pregnancy BMI <25 and >12 kg for participants with pre-pregnancy BMI ≥25 | Excessive GWG; Multivariable Poisson log-linear regression; RR (95% CI); [underlined: 3 dietary risk factors score]; per SD: 1.08 (1.002, 1.15), p<0.05; [underlined: 6 dietary risk factors score]; Per one unit: 1.10 (1.01, 1.19), p<0.05; Per SD: 1.08 (1.01, 1.15), p<0.05; T2 vs. T1 (Ref): 1.04 (0.86, 1.26), p=NS; T3 vs. T1 (Ref):1.23 (1.002, 1.50), p<0.05; Stratifying by BMI attenuated the results; Excluding 264 GDM cases:; Per one unit: 1.09 (1.00, 1.19), p=NS; T2 vs. T1 (Ref): 1.01 (0.82, 1.23), p=NS; T3 vs. T1 (Ref): 1.19 (0.96, 1.47), p=NS; Stratifying by BMI did not substantially alter the results; [underlined: 13 dietary risk factors score]; per SD: 1.04 (0.97, 1.22), p=NS | Key confounders accounted for: Age, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity, DM in the current pregnancy (in sensitivity analyses; Key confounders not accounted for: Physical activity, Race and/or ethnicity, HDP in the current pregnancy; Other covariates: Gestation length when highest weight recorded, NVP; Limitations: Issues with confounding, missing data, and selection of the reported results; some concerns about exposure measurement, participant selection, and outcome measurement; Funding: Doctoral Grants of the UoI Research Fund; The Technology Development Fund/RANNIS
Jayedi, 2023 ^199^; PCS, Iran (Islamic Rep. of), PERSIAN (Semnan branch); Analytic N =657; - Age (y): 28.8±5.08; - Socioeconomic position:; ○ Job with income (%): PDI: Q1: 31.8; Q4: 25.3 hPDI: Q1: 28.3; Q4: 26.9 uPDI: Q1: 30.8; Q4: 33.3; ○ University graduate: PDI: Q1: 5.30; Q4: 4.00 hPDI: Q1: 5.30; Q4: 4.00 uPDI: Q1: 5.90; Q4: 3.60; - Pre-pregnancy BMI: PDI: Q1: 25.8±5.04; Q4: 24.7±4.11, p<0.001 hPDI: Q1: 24.5±4.12; Q4: 25.3±4.79 uPDI: Q1: 25.0±4.50; Q4: 24.6±3.83; - Smoking (%): 0.0 | PDI, hPDI, & uPDI (quartiles of alignment); FFQ at: TM1; DP Descriptions:; [underlined: PDI:]; - Positive components: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); less healthy plant-based foods (fruit juices, refined grains, potatoes, sugar-sweetened beverages, sweets/desserts); - Negative components: animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods); [underlined: hPDI:]; - Positive components: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); - Negative components: less healthy plant-based foods (fruit juices, refined grains, potatoes, sugar-sweetened beverages, sweets/desserts); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods); [underlined: uPDI:]; - Positive components: less healthy plant-based foods (fruit juices, refined grains, potatoes, sugar-sweetened beverages, sweets/desserts); - Negative components: healthy plant-based foods (whole grains, fruits, vegetables, nuts, legumes, vegetable oils, tea/coffee); animal-based foods (animal fat, dairy, eggs, fish/seafood, meat, miscellaneous animal-based foods); Outcome and assessment methods:; GWG assessed at: TM1 to before delivery; Investigators measured weight and height. GWG: difference in weight between TM1 and delivery. GWG adequacy by 1990 IOM recommendations. Inadequate GWG below and Excessive GWG below: BMI <18.5: 12.8–18 kg; BMI 18.5–24.9: 11.5–16 kg; BMI 25–29.9: 7–11.5 kg; BMI ≥30: 5–9 kg | Inadequate GWG; Cox proportional-hazards; HR (95% CI); [underlined: PDI]; Q4 vs Q1 (Ref): 0.50 (0.29,0.89), p=0.02; Q3 vs Q1 (Ref): 0.73 (0.42, 1.25), p=0.25; Q2 vs Q1 (Ref): 0.79 (0.45, 1.41), p=0.43; [underlined: hPDI]; Q4 vs Q1 (Ref): 1.15 (0.66, 1.91), p=0.62; Q3 vs Q1 (Ref): 1.15 (0.66, 1.98), p=0.63; Q2 vs Q1 (Ref): 1.26 (0.70, 2.27), p=0.43; [underlined: uPDI]; Q4 vs Q1 (Ref): 0.75 (0.42, 1.34), p=0.33; Q3 vs Q1 (Ref): 0.67 (0.38, 1.13), p=0.13; Q2 vs Q1 (Ref): 0.62 (0.34, 1.10), p=0.10; Excessive GWG; Cox proportional-hazards; HR (95% CI); [underlined: PDI]; Q4 vs Q1 (Ref): 0.99 (0.69, 1.42), p=0.96; Q3 vs Q1 (Ref): 1.03 (0.73, 1.48), p=0.83; Q2 vs Q1 (Ref): 1.08 (0.77, 1.50), p=0.65; [underlined: hPDI]; Q4 vs Q1 (Ref): 0.91 (0.66, 1.27), p=0.58; Q3 vs Q1 (Ref): 0.95 (0.68, 1.33), p=0.79; Q2 vs Q1 (Ref): 1.24 (0.88, 1.74), p=0.22; uPDI; Q4 vs Q1 (Ref): 1.17 (0.82, 1.65), p=0.38; Q3 vs Q1 (Ref): 0.90 (0.65, 1.25), p=0.54; Q2 vs Q1 (Ref): 0.88 (0.63, 1.24), p=0.47 | Key confounders accounted for: Age, Physical activity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity; Key confounders not accounted for: Race and/or ethnicity, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: TEI, pre-pregnancy supplement intake, multivitamin use during pregnancy, history of cardiovascular disease; Limitations: Issues with missing data, selection of the reported results; some concerns about confounding; Funding: Semnan University of Medical Sciences
Liu, 2023 ^195^; PCS, United States, PETALS; Analytic N =2914; - Age (%): 18–24y: 15.2; 25–29y: 25.9; 30–34y: 36.8; ≥35y: 22.1; - Race/Ethnicity (%): AAPI: 24; Black: 9.6; Hispanic: 40; Other/Unknown: 3.2; NHW: 23; - Socioeconomic position:; ○ Education (%): <High school: 2.7; Some college: 37; ≥4y college: 49; ○ Household income (%): <$50,000/y: 32; ≥$150,000/y: 18; - Pre-pregnancy BMI: 27.0±6.0; - DM/HDP (%); ○ DM: 0.0 | HEI-2010, DASH, aMED, and EDIP (quartiles of alignment); FFQ at: ∼10–13 GW; DP Descriptions (alcohol components excluded):; [underlined: HEI-2010:]; - Positive components: total fruit, whole fruit, total vegetables, greens and beans, whole grains, dairy, total protein foods, seafood and plant proteins, fatty acids; - Negative components: refined grains, sodium, and empty calories; [underlined: DASH:]; - Positive components: fruits, vegetables, nuts and legumes, low-fat dairy products, whole grains; - Negative components: sodium, red and processed meats, and sweetened beverages; [underlined: aMED:]; - Positive components: fish, whole grains, legumes, nuts, fruits, vegetables, and monounsaturated to saturated fat ratios; - Negative components: red and processed meat; [underlined: EDIP:]; - Positive components: Tea, coffee, dark yellow vegetables, leafy green vegetables, snacks, fruit juice, pizza; - Negative components: processed meat, red meat, organ meat, other fish, other vegetables, refined grains, high-energy beverages, low-energy beverages, and tomatoes; Outcome and assessment methods:; GWG assessed at: ∼10–13 GW to delivery; GWG difference between weight at delivery and visit 1. GWGR calculated by dividing GWG by the number of weeks btw the two measurements. GWGR adequacy by 2009 lOM-recommendations. | Excessive GWGR; Multivariable Poisson Regression; Adjusted RR (95% CI); [underlined: HEI-2010]; Q1 vs Q4 (Ref): 1.04 (1.00, 1.07), p ≤0.05; Q2 vs Q4 (Ref): 1.05 (1.01, 1.08), p ≤0.05; Q3 vs Q4 (Ref): 1.01 (0.98, 1.05), p>0.05; BMI <25.0: Q1 vs Q4 (Ref): 1.05 (1.00,1.10), p≤0.05; 25.0≤BMI≤ 29.9: Q1 vs Q4 (Ref): 1.04 (0.97, 1.06), p>0.05; BMI≥30.0: Q1 vs Q4 (Ref): 1.01 (0.97, 1.06), p>0.05; AAPI: Q1 vs Q4 (Ref): 1.00 (0.94, 1.06), p>0.05; Black: Q1 vs Q4 (Ref): 1.14 (1.02,1.28), p≤0.05; Hispanic: Q1 vs Q4 (Ref): 0.99 (0.95, 1.03), p>0.05; Other/Unknown: Q1 vs Q4 (Ref): 1.15 (0.99,1.35), p>0.05; NHW: Q1 vs Q4 (Ref): 1.07 (1.01,1.12), p≤0.05; [underlined: DASH]; Q1 vs Q4 (Ref): 1.00 (0.97, 1.04), p>0.05; Q2 vs Q4 (Ref): 1.02 (0.99, 1.06), p>0.05; Q3 vs Q4 (Ref): 1.03 (0.99, 1.06), p>0.05; [underlined: aMED]; Q1 vs Q4 (Ref): 1.00 (0.96, 1.04), p>0.05; Q2 vs Q4 (Ref): 1.00 (0.96, 1.04), p>0.05; Q3 vs Q4 (Ref): 1.02 (0.99, 1.05), p>0.05; [underlined: EDIP]; Q4 vs Q1 (Ref): 1.00 (0.97, 1.03), p>0.05; Q3 vs Q1 (Ref): 0.98 (0.95, 1.01), p>0.05; Q2 vs Q1 (Ref): 0.99 (0.96, 1.03), p>0.05; Inadequate GWGR; Multivariable Poisson Regression; Adjusted RR (95% CI); [underlined: HEI-2010]; Q1 vs Q4 (Ref): 0.92 (0.82, 1.03), p>0.05; Q2 vs Q4 (Ref): 0.98 (0.88, 1.10), p>0.05; Q3 vs Q4 (Ref): 0.96 (0.86, 1.07), p>0.05; [underlined: DASH]; Q1 vs Q4 (Ref): 0.96 (0.85, 1.08), p>0.05; Q2 vs Q4 (Ref): 0.97 (0.87, 1.09), p>0.05; Q3 vs Q4 (Ref): 0.91 (0.81, 1.02), p>0.05; [underlined: aMED]; Q1 vs Q4 (Ref): 1.07 (0.94, 1.21), p>0.05; Q2 vs Q4 (Ref): 1.05 (0.92, 1.19), p>0.05; Q3 vs Q4 (Ref): 1.04 (0.94, 1.15), p>0.05; [underlined: EDIP]; Q4 vs Q1 (Ref): 0.92 (0.83, 1.03), p>0.05; Q3 vs Q1 (Ref): 0.90 (0.81, 1.00), p>0.05; Q2 vs Q1 (Ref): 0.93 (0.84, 1.03), p>0.05 | Key confounders accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Parity, DM in the current pregnancy; Key confounders not accounted for: Smoking, HDP in the current pregnancy; Other covariates: TEI; Limitations: Some concerns about confounding, missing data, selection of the reported results; Funding: NIEHS; NIH’s ECHO
Radwan, 2021 ^200^; PCS, United Arab Emirates, MISC; Analytic N =243; - Age (%): 18–24.9y: 22.6; 25–34.9y: 51.4; ≥35y: 25.9; - Race/Ethnicity (%): Nationality: Emirati: 40.7; Arab: 59.3; - Socioeconomic position:; ○ Education (%): ≤Intermediate: 13.2; University: 32.1; ○ Employment (%): Homemaker: 81.9; Employee: 18.1; ○ Income (%): <10,000 AED: 35.0; ≥10,000 AED: 40.7; Don’t know: 24.3; - DM/HDP (%):; ○ GDM: 19.3; ○ PE: 0.0 | aMED & LMD (low vs high alignment); FFQ at: ≥27 GW; DP Descriptions:; [underlined: aMED:]; - Positive components: vegetables (not potatoes); legumes; fruit; Nuts; whole grains; fish; MUFA/SFA.; - Negative components: red and processed meat; [underlined: Lebanese Mediterranean Diet (LMD):]; - Positive components: whole grains/bulgur; olive oil; fruits; dried fruits; vegetables; Starchy vegetables; legumes; eggs, dairy; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; GWGR assessed at: 12 GW to delivery; GWG extracted from medical records. GWGR calculated based on assumption that 1 kg gained in TM1. GWG and GWGR adequacy by 2009 IOM recommendations. | GWG Adequacy; Logistic regression; OR (95% CI); [underlined: aMED]; Inadequate: High vs low (Ref): 0.31 (0.11, 0.83), p<0.05; Excessive: High vs low (Ref): 0.41 (0.18, 0.93), p<0.05; [underlined: LMD]; Inadequate: High vs low (Ref): 0.48 (0.18, 1.34), p=NS; Excessive: High vs low (Ref): 0.40 (0.16, 0.98), p<0.05; GWGR Adequacy; Logistic regression; OR (95% CI); [underlined: aMED]; Inadequate: High vs low (Ref): 0.46 (0.2, 1.04), p=NS; Excessive: High vs low (Ref): 0.52 (0.23, 1.15), p=NS; [underlined: LMD]; Inadequate: High vs low (Ref): 0.47 (0.2, 1.1), p=NS; Excessive: High vs low (Ref): 0.34 (0.14, 0.81), p<0.05 | Key confounders accounted for: Age, Pre-pregnancy BMI, Parity, HDP in the current pregnancy; Key confounders not accounted for: Physical activity, Race and/or ethnicity, Socioeconomic position, Smoking, DM in the current pregnancy; Other covariates: TEI; Limitations: Issues with confounding, missing data; some concerns about exposure measurement, participant selection; Funding: Al Jalila Foundation; Vice-Chancellor Research and Graduate Studies Office/University of Sharjah Grant
Rifas-Shiman, 2009 ^187^; PCS, United States, Project Viva; Analytic N=1777; - Age: 32.4± 4.9y; - Race/Ethnicity (%): White: 72; Black/African American: 12; Other, > 1 race: 16; - Socioeconomic position:; ○ Education (%): ≤High school: 9; College graduate: 69; ○ Household income (%): <$40,000/y: 13; - Pre-pregnancy BMI: 24.6± 5.3; - DM/HDP (%):; ○ GDM: 5.0 | AHEI-P (continuous alignment); FFQ at: TM1 (∼11wk) and TM2 (∼26–28wk); DP Description:; - Positive components: Vegetables; fruit; white to red meat ratio; fiber; PUFA/SFA; folate; calcium; iron; - Negative component: Trans fat; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to last clinical weight; Pre-pregnancy weight self-reported at baseline. Last clinical weight taken from medical records. GWG adequacy by 1990 IOM recommendations | Inadequate GWG; Multinomial logistic regression; OR (95% CI); TM1 AHEI-P: 0.95 (0.88, 1.02), p=NS; TM2 AHEI-P: 0.99 (0.92, 1.07), p=NS; Excessive GWG; Multinomial logistic regression; OR (95% CI); TM1 AHEI-P: 0.99 (0.94, 1.04), p=NS; TM2 AHEI-P: 0.99 (0.94, 1.04), p=NS | Key confounders accounted for: Age, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Parity; Key confounders not accounted for: Physical activity, Smoking, DM in the current pregnancy, HDP in the current pregnancy; Other covariates:; Limitations: Issues with confounding, participant selection, missing data, and selection of the reported results; some concerns about exposure measurement, deviations from intended interventions, and outcome measurement; Funding: NIH; Harvard Medical School; Harvard Pilgrim Health Care Foundation
Silva-del Valle, 2013 ^206^; RCS, Spain, University Hospital Materno Infantil of Gran Canaria; Analytic N =170; - Age (%): 16–20y: T1: 4.5; T3: 4.3; 21–25y: T1: 31.8; T3: 8.7 26–30y: T1: 43.2; T3: 39.1 >31y: T1: 20.5; T3: 47.8; - Race/Ethnicity (%): White Spanish: 100; - Socioeconomic position:; ○ Education (%): Lower: T1: 54.5; T3: 26.3; Intermediate: T1: 27.3; T3: 31.6; Higher: T1: 18.2; T3: 42.1; - Pre-pregnancy BMI: T1: 25.1±4.5; T3: 24.3±4.7 | Med Diet (continuous alignment, tertiles of alignment); FFQ at: First prenatal visit; DP Description:; - Positive components: olive oil as principal fat; olive oil servings; vegetables; fruit; pulses; fish, seafood; nuts; chicken, turkey, or rabbit in place of red meat or sausages; sofrito; wine.; - Negative components: red meat/sausages; butter, margarine, cream; carbonated and/or sugar-sweetened beverages; commercial pastries; Outcome and assessment methods:; GWG assessed at: Prepregnancy to delivery; Self-reported pre-pregnancy weight and height at first prenatal visit. Pregnancy weights from medical records. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Logistic regression; OR (95% CI); Per one point: 1.38 (1.07, 1.79); T3 vs T1 (Ref): 10.35 (1.80, 59.54); T2 vs T1 (Ref): 4.16 (0.84, 20.66); Adequate GWG; Logistic regression; OR (95%CI); Per one point: 0.91 (0.76, 1.09); T3 vs T1 (Ref): 0.59 (0.19, 1.82); T2 vs T1 (Ref): 1.01 (0.38, 2.74); Excessive GWG; Logistic regression; OR (95% CI); Per one point: 0.98 (0.80, 1.20); T3 vs T1 (Ref): 0.82 (0.23, 2.92); T2 vs T1 (Ref): 0.50 (0.17, 1.48) | Key confounders accounted for: Age, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI; Key confounders not accounted for: Physical activity, Smoking, Parity, DM in the current pregnancy, HDP in the current pregnancy; Other covariates:; Limitations: Issues with confounding, missing data; some concerns about exposure measurement, participant selection, and selection of the reported results; Funding: NR
Tielemans, 2015 ^188^; PCS, Netherlands, Generation R Study; Analytic N=2748; - Age: ∼31.3y; - Race/Ethnicity (%): Dutch ancestry: 100; - Socioeconomic position:; ○ Education (%): Low and midlow: ∼18.2; High: ∼30.4; ○ Household income (%): <2200 Euro/mo: ∼28.3; - Pre-pregnancy BMI: ∼24.7; - Smoking (%): Until pregnancy known: ∼8.3; During pregnancy: ∼17.4; - DM/HDP (%):; ○ GDM: 11.0; ○ HDP: 7.4 | Dutch Healthy Diet Index (continuous alignment, quartiles of alignment); FFQ at ∼13.4wk; DP Description:; - Positive components: vegetables, fruits, fiber, and fish; - Negative components: saturated fat and sodium; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to maximum pregnancy weight; Self-reported pre-pregnancy weight collected at enrollment. Self-reported maximum pregnancy weight collected at 6wk postpartum. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Multinomial logistic regression; OR (95% CI); Per SD: p=0.07; Q2 vs. Q1 (Ref): 1.04 (0.74, 1.45), p=NS; Q3 vs. Q1 (Ref): 0.84 (0.59, 1.20), p=NS; Q4 vs. Q1 (Ref): 1.32 (0.92, 1.90), p=NS; Excessive GWG; Multinomial logistic regression; OR (95% CI); Per SD: p=0.66; Q2 vs. Q1 (Ref): 0.92 (0.69, 1.24), p=NS; Q3 vs. Q1 (Ref): 0.95 (0.70, 1.27), p=NS; Q4 vs. Q1 (Ref): 1.11 (0.80, 1.53), p=NS | Key confounders accounted for: Age, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity, DM in the current pregnancy, HDP in the current pregnancy; Key confounders not accounted for: Physical activity; Other covariates: Alcohol consumption during pregnancy, Stress during pregnancy, Fetal sex; Limitations: Issues with confounding, outcome measurement, and selection of the reported results; some concerns about exposure measurement, participant selection; Funding: Erasmus Medical Center; University Medical Centre Rotterdam; the Erasmus University, Rotterdam; the Dutch Ministry of Health, Welfare and Sport; the Netherlands Organization for Health Research and Development; Nestlé Nutrition; Metagenics Inc.
Yang, 2022 ^197^; PCS, China, Sichuan Provincial Hospital for Women and Children; Analytic N =1416; - Age (y): IWG: 29.5±4.0; AWG: 28.8±4.1; EWG: 28.3±4.0; - Socioeconomic position:; ○ Education (%): ≤Secondary level: IWG: 21.2; AWG: 20.6; EWG: 27.1; Graduate: IWG: 10.0; AWG: 6.5; EWG: 5.4, p=0.016; ○ Household Income (%): ≤451.65 USD/mo: IWG: 3.5; AWG: 3.3; EWG: 3.7; ≥1506.00 USD/mo: IWG: 21.8; AWG: 19.9; EWG: 22.3; - Pre-pregnancy BMI: IWG: 22.0±3.3; AWG: 20.7±2.6; EWG: 21.1±2.6;; ○ (%): <18.5: IWG: 17.1; AWG: 16.7; EWG: 11.4; ≥24: IWG: 21.2; AWG: 8.5; EWG: 14.2, p=0.001; - DM/HDP (%):; ○ Pre-GDM: 0.0; - Smoking (%): IWG: 1.8; AWG: 3.1; EWG: 4.5 | CHDI-P (tertiles of alignment); 24 hr recall at: 6–14 GW, 24–28 GW, 32–36 GW; DP Description:; - Positive components: grains, tubers and mixed beans; vegetables and fruits; meat, poultry, fish and eggs; dairy, soybeans and nuts; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; Pre-pregnancy weight self-reported. Delivery weight measured. GWG adequacy by 2009 IOM recommendations. | EWG; Multiple logistic regression; OR (95% CI); [underlined: CHDI-P at 6–14 GW (n=1416)]; T1 vs. T3 (Ref): 0.86 (0.65, 1.14), p=0.29; T2 vs T3 (Ref): 0.90 (0.68, 1.19), p=0.48; [underlined: CHDI-P at 24–28 GW (n=971)]; T1 vs. T3 (Ref): 1.53 (1.08,2.17), p=0.02; T2 vs. T3 (Ref): 1.06 (0.75, 1.49), p=0.74; [underlined: CHDI-P at 32–36 GW (n=997)]; T1 vs. T3 (Ref): 1.71 (1.21,2.41), p=0.002; T2 vs T3 (Ref): 1.59 (1.13, 2.23), p=0.008; IWG; Multiple logistic regression; OR (95% CI); [underlined: CHDI-P at 6–14 GW (n=1416)]; T1 vs T3 (Ref): 1.32 (0.85, 2.06), p=0.22; T2 vs T3 (Ref): 1.40 (0.90, 2.18), p=0.13; [underlined: CHDI-P at 24–28 GW (n=971)]; T1 vs T3 (Ref): 1.20 (0.72,1.99), p=0.48; T2 vs T3 (Ref): 0.79 (0.47, 1.31), p=0.36; [underlined: CHDI-P at 32–36 GW (n=997)]; T1 vs T3 (Ref): 0.65 (0.38,1.12), p=0.12; T2 vs T3 (Ref) : 0.75 (0.45, 1.25), p=0.27 | Key confounders accounted for: Age, Physical activity, Pre-pregnancy BMI; Key confounders not accounted for: Race and/or ethnicity, Socioeconomic position, Smoking, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: Primigravida (yes/no); Limitations: Issues with confounding, missing data; some concerns about selection of the reported results; Funding: Danone Nutrition Centre for dietary nutrition research and Education
Yong, 2019 ^192^; PCS, Malaysia, SECOST; Analytic N=480; - Age: 30.16± 4.51y; - Race/Ethnicity (%): Malay: 89.0; Non-Malay: 11.0; - Socioeconomic position:; ○ Education (y): 12.95± 2.41; ■ (%): ≤Secondary: 46.0; ≥Tertiary and above: 21.3; ○ Employed (%): 69.2; ○ Monthly household income (RM): 3698.30± 2034.20; ■ (%): Low: 63.5; High: 2.9; ○ Household size: 3.78±1.63; ■ (%): ≤2: 24.2; ≥5: 25.8%; - Pre-pregnancy BMI: 24.10± 5.06; ○ (%): <18.5: 10.2; 25–29.9: 22.3; ≥30: 14.4 | HEI for Malaysians (continuous alignment); 24 hr recall at: TM1, TM2, and TM3; DP Description:; - Positive components: Cereals and grains (6–8 svg/d); vegetables (≥3 svg/d); fruits (2 svg/d); milk and milk products (2–3 svg/d); poultry, meat, and eggs (1–2 svg/d); fish and seafood (1 svg/d); legumes (1 svg/d); - Negative components: %E from fat; sodium; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to last visit; Pre-pregnancy weight self-reported. Last weight measured using standard instrument and procedures. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Multinomial logistic regression; OR (95% CI); [underlined: All participants]; TM1 HEI: 1.01 (0.99, 1.02), p=0.68; TM2 HEI: 0.98 (0.96, 0.98), p=0.03; TM3 HEI: 0.99 (0.97, 1.01), p=0.60; [underlined: Pre-pregnancy BMI <25]; TM1 HEI: 1.01 (0.98, 1.03), p=0.74; TM2 HEI: 0.97 (0.95, 0.99), p=0.01; TM3 HEI: 0.99 (0.97, 1.01), p=0.27; [underlined: Pre-pregnancy BMI >25]; TM1 HEI: 1.01 (0.97, 1.04), p=0.69; TM2 HEI: 1.00 (0.96, 1.03), p=0.82; TM3 HEI: 1.01 (0.97, 1.05), p=0.50; Excessive GWG; Multinomial logistic regression; OR (95% CI); [underlined: All participants]; TM1 HEI: 1.02 (0.99, 1.03), p=0.52; TM2 HEI: 1.01 (0.98, 1.03), p=0.33; TM3 HEI: 1.04 (1.01, 1.06), p=0.01; [underlined: Pre-pregnancy BMI <25]; TM1 HEI: 1.02 (0.99, 1.05), p=0.34; TM2 HEI: 0.99 (0.96, 1.02), p=0.44; TM3 HEI: 1.04 (1.01, 1.07), p=0.03; [underlined: Pre-pregnancy BMI >25]; TM1 HEI: 0.99 (0.97, 1.03), p=0.95; TM2 HEI: 1.04 (1.01, 1.07), p=0.02; TM3 HEI: 1.04 (1.01, 1.08), p=0.02 | Key confounders accounted for: Age, Physical activity, Socioeconomic position, Pre-pregnancy BMI, Parity,; Key confounders not accounted for: Race and/or ethnicity, Smoking, DM in the current pregnancy, HDP in the current pregnancy; Other covariates:; Limitations: Issues with confounding, participant selection, selection of the reported results; some concerns about exposure measurement, outcome measurement; Funding: DANONE DUMEX (M) SDN BHD
Factor/Cluster Analysis
Berube, 2023 ^196^; PCS, United States, StEP; Analytic N =500; - Age (y): Western T1: 30±6; Western T3: 27±5, p<0.0001 F&V T1: 27±6; F&V T1: 29±6, p<0.05; - Race/Ethnicity (%): Hispanic/Latina: 100; - Socioeconomic position:; ○ Education (%): <High school: 33.6; ≥High school: 66.4; ○ Employed (%): 24.8; - Pre-pregnancy BMI: 27.5±5.5 | Western and F&V DP (tertiles of alignment); FFQ at: At baseline (28–32 GW); DP Descriptions:; - Western DP: Characterized by higher intake of cakes, pies and cookies, processed meats, American dishes, candy, sweetened beverages, and salty snacks; - Fruits and vegetables (F&V) DP: Characterized by higher intake of nonstarchy vegetables, starchy vegetables, beans and peas, meat/vegetable soups, whole fresh fruit; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; Pre-pregnancy weight (first measured weight at ≤12 GW) and weight at delivery were extracted from medical records. If the first measured weight taken at >12 GW, self-reported pre-pregnancy weight was used. GWG calculated by subtracting pre-pregnancy weight from weight at delivery. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Multinomial logistic regression; OR (95% CI); [underlined: Western DP]; T1: Ref; T2: 0.7 (0.4, 1.3); T3: 0.8 (0.4, 1.8), p>0.05; [underlined: F&V DP]; T1: Ref; T2: 1.1 (0.6, 1.8); T3: 1.1 (0.6, 2.1), p>0.05; Excessive GWG; Multinomial logistic regression; OR (95% CI); [underlined: Western DP]; T1: Ref; T2: 0.9 (0.5, 1.6); T3: 1.2 (0.5, 3.0), p>0.05; [underlined: F&V DP]; T1: Ref; T2: 1.1 (0.6, 1.9); T3: 1.2 (0.5, 2.2), p>0.05 | Key confounders accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Parity; Key confounders not accounted for: Smoking, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: TEI; Limitations: Issues with post-exposure interventions; some concerns about confounding, exposure measurement, participant selection, and selection of the reported results; Funding: USDA NIFA, NICHD, HRSA
Hu, 2022 ^204^; PCS, China, BISCS; Analytic N =1026; - Age (%): <25y: Non-EGWG: 5.5; EGWG: 6.1; ≥35y: Non-EGWG: 17.0; EGWG: 13.9; - Race/Ethnicity (%): Han ethnicity: Non-EGWG: 85.8; EGWG: 81.1; Minority: Non-EGWG: 14.2; EGWG: 18.9, p=0.04; - Socioeconomic position:; ○ Education (%):≤High school: Non-EGWG: 19.1; EGWG: 27.5; ≥College: Non-EGWG: 80.9; EGWG 72.5, p≤0.01; ○ Household income (%): <50,000 CNY/y: Non-EGWG: 51.5; EGWG: 54.5; ≥50,000 CNY/y: Non-EGWG: 48.5; EGWG: 45.6; - Pre-pregnancy BMI: (%): <18.5: Non-EGWG: 17.7; EGWG: 8.9; ≥25: Non-EGWG: 12.7; EGWG: 24.1, p≤0.01; - Smoking before or during pregnancy (%): Non-EGWG: 0.4; EGWG: 0.7 | Traditional DP, Sweet foods DP, High protein DP, & MNS DP (quartiles of alignment); Food Diary at: 22±1.2 GW; DP Descriptions:; - Traditional DP: Characterized by high intakes of tubers; vegetables; fruits; red meat; rice; - Sweet foods DP: Characterized by high intakes of sweet beverages; pastry and candy; shrimps, crabs and mussels; fruits; - High protein DP: Characterized by high intakes of fried foods; beans and bean products; dairy products; fruits; - Milk-nut-seafood (MNS) DP: Characterized by high intakes of milk; nuts; shrimps, crabs and mussels; fruits; dairy products; eggs and egg; pastry and candy; and a lower intake of sweet beverages; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy weight to last measured weight. Pre-pregnancy weight self-reported. Pregnancy weight measured by investigators. GWG: difference between the last measured and pre-pregnancy weight. GWG adequacy by 2009 IOM recommendations. | Excessive GWG; Logistic regression; OR (95% CI); [underlined: Traditional DP]; Q4: 1.67 (1.04, 2.67); Q3: 1.62 (1.10, 2.40); Q2: 1.06 (0.73, 1.54); Q1 (Ref); p-for trend= 0.02; [underlined: Sweet foods DP]; Q4: 0.94 (0.65, 1.37); Q3: 1.03 (0.71, 1.49); Q2: 0.66 (0.46, 0.95); Q1 (Ref); p-for trend= 0.79; [underlined: High protein DP]; Q4: 0.67 (0.46, 0.99); Q3: 0.56 (0.38, 0.81); Q2: 0.66 (0.46, 0.96); Q1 (Ref); p-for trend=0.10; [underlined: MNS DP]; Q4: 1.04 (0.70, 1.53); Q3: 0.94 (0.65, 1.37); Q2: 0.83 (0.58, 1.20); Q1 (Ref); p-for trend=0.64 | Key confounders accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity; Key confounders not accounted for: DM in the current pregnancy, HDP in the current pregnancy; Other covariates: TEI; Other DP score; Limitations: Issues with missing data; some concerns about confounding, selection of the reported results; Funding: National Natural Science Foundation of China; Department of Science & Technology of Liaoning Province
Itani, 2020 ^201^; PCS, United Arab Emirates, MISC; Analytic N =242; - Age (%): 18–24.9y: 22.7; 25–29.9y: 25.2; ≥30y: 52.1; - Race/Ethnicity (%): Nationality: Emiratis: 40.9; Arabs: 59.1; - Socioeconomic position:; ○ Education (%): ≤Primary: 12.8; Intermediate/high school: 55.4; University: 31.8; ○ Family income (%): <10,000 AED/mo: 47.0; >10,000 AED/mo: 53.0; - Pre-pregnancy BMI (%): <25: 40.1; ≥25: 59.9; - DM/HDP (%):; ○ GDM: 19.8;; ○ T1 or T2 DM: 0.0;; ○ HTN or PE: 0.0 | Diverse DP & Western DP (quartiles of alignment); FFQ at: 27–42 GW; DP Descriptions:; - Diverse DP: High in fruits, vegetables, mixed dishes, meats, dairy, grains, legumes and nuts, fats and oils; - Western DP: High in sweets, sweetened beverages, added sugars, fast food, eggs, offals; Outcome and assessment methods:; GWG assessed at: pre-pregnancy to delivery; GWG: last weight from medical records measured before delivery minus pre-pregnancy weight. GWG adequacy by 2009 IOM recommendations. | Insufficient GWG; Logistic regression; OR (95% CI); [underlined: Diverse DP]; Q4 vs Q1 (Ref): 0.24 (0.06, 0.97), p<0.05; Q3 vs Q1 (Ref): 0.33 (0.09, 1.21), p=NS; Q2 vs Q1 (Ref): 0.33 (0.09, 1.17), p=NS; [underlined: Western DP]; Q4 vs Q1 (Ref): 1.73 (0.4, 7.55), p=NS; Q3 vs Q1 (Ref): 1.43 (0.46, 4.48), p=NS; Q2 vs Q1 (Ref): 0.95 (0.29, 3.10), p=NS; Excessive GWG; Logistic regression; OR (95% CI); [underlined: Diverse DP]; Q4 vs Q1 (Ref): 0.40 (0.11, 1.43), p=NS; Q3 vs Q1 (Ref): 0.40 (0.12, 1.31), p=NS; Q2 vs Q1 (Ref): 0.38 (0.12, 1.22), p=NS; [underlined: Western DP]; Q4 vs Q1 (Ref):4.04 (1.07, 15.24), p<0.05; Q3 vs Q1 (Ref): 1.67 (0.5, 4.84), p=NS; Q2 vs Q1 (Ref): 2.01 (0.71, 5.72), p=NS | Key confounders accounted for: Age, Pre-pregnancy BMI, Parity, DM in the current pregnancy, HDP in the current pregnancy; Key confounders not accounted for: Physical activity, Race and/or ethnicity, Socioeconomic position, Smoking; Other covariates: TEI; Limitations: Some concerns about confounding, exposure measurement, participant selection, and selection of the reported results; Funding: Al Jalila Foundation; University of Sharjah
Jarman, 2018 ^202^; PCS, Canada, APrON; Analytic N =1545; - Age (y): 31.4±4.2; - Race/Ethnicity (%): White: 84; - Socioeconomic position:; ○ Education (%): <University: 28; University: 72; ○ Household income (%): <$100,000/y: 42; ≥$100,000/y: 58; - Pre-pregnancy BMI (%): <18.5: 3; 18.5–24.9: 65; 25–29.9: 21; ≥30: 11; - DM/HDP (%):; ○ GDM: 3.0; ○ HDP: 6.0; - Smoking (%): 1.0 | Tea and Coffee DP (continuous alignment); FFQ at: Median: 17 GW; DP Description:; - Tea and Coffee DP: Higher in coffee, tea (both regular and decaffeinated), reduced-fat milk, full-fat milk, cream and added sugar; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to highest pregnancy weight.; In cases in which the participant did not report their highest weight or reported a weight that was lower than had been measured during TM3, GWG calculated using measured weight in TM3. Excessive GWG by 2009 IOM recommendations. | Excessive GWG; Forward step-wise logistic regression OR (95% CI); 1.1 (0.98, 1.3), p=0.07 | Key confounders accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity; Key confounders not accounted for: DM in the current pregnancy, HDP in the current pregnancy; Other covariates: TEI; Limitations: Issues with missing data; some concerns about confounding, selection of the reported results; Funding: Alberta Innovates Health Solutions
Li, 2021 ^194^; PCS, China, Tongji MCHC; Analytic N =3334; - Age (y): 28.1±3.5; - Race/Ethnicity (%): Han ethnicity: 97.0; - Socioeconomic position:; ○ Education (%): ≤9y: 3.5; 10–12y: 13.2; ≥16y: 53.9;; ○ Average personal income (%): ≤1000 CNY/mo: 0.4; 1001–2999 CNY/mo: 7.5; ≥10,000 CNY/mo: 16.2;; - Pre-pregnancy BMI: 20.77±2.71; ○ (%): <18.5: 20; 24–27.9: 10.0; ≥28: 1.7; - Smoking (%): Pre-pregnancy: 3.6 | BV DP, FME DP, NWG DP, OPS DP, & RWF DP (continuous alignment, quartiles of alignment); FFQ at: 24–28 GW; DP Descriptions:; - Beans-vegetables (BV) DP: Higher in root vegetables; mushrooms and algae; melon and solanaceous vegetables; beans and bean products (soybean, mung bean, soybean milk, bean curd, etc); leafy and cruciferous vegetables; - Fish-meat-eggs (FME) DP: Higher in red meat; freshwater fishes; eggs; - Nuts-whole grains (NWG) DP: Higher in nuts; whole grains, dairy products; - Organ-poultry-seafood (OPS) DP: Higher in animal organ and blood; seafood; poultry; - Rice-wheat-fruits (RWF) DP: Higher in rice and wheat products; fruits; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; GWG: investigator-measured weight at delivery minus self-reported pre-pregnancy weight. GWG adequacy by 2009 IOM recommendations | Excessive GWG; Logistic regression; OR (95% CI); [underlined: BV DP:] 0.84 (0.77, 0.91), p<0.001; [underlined: FME DP:] 1.07 (0.99. 1.16), p>0.05; [underlined: NWG DP:] 1.07 (0.99. 1.15), p>0.05; [underlined: OPS DP:] 0.94 (0.87, 1.01), p>0.05; [underlined: RWF DP:] 1.01 (0.92, 1.12), p>0.05; Adequate GWG; Logistic regression; OR (95% CI); [underlined: BV DP:] 1.11 (1.03, 1.21), p<0.05; [underlined: FME DP:] 1.04 (0.96, 1.13), p>0.05; [underlined: NWG DP:] 1.02 (0.94, 1.11), p>0.05; [underlined: OPS DP:] 1.04 (0.96, 1.12), p>0.05; [underlined: RWF DP:] 1.14 (1.02, 1.26), p<0.05; Insufficient GWG; Logistic regression; OR (95% CI); [underlined: BV DP:] 1.14 (1.03, 1.26), p<0.05; [underlined: FME DP:] 0.85 (0.77, 0.95), p<0.05; [underlined: NWG DP:] 0.87 (0.79, 0.96), p<0.05; [underlined: OPS DP:] 1.06 (0.96, 1.17), p>0.05; [underlined: RWF DP:] 0.83 (0.74, 0.93), p<0.05 | Key confounders accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity, DM in the current pregnancy; Key confounders not accounted for: HDP in the current pregnancy; Other covariates: Ethnology, family history of diabetes, family history of obesity, alcohol consumption before pregnancy, other 4 DP; Limitations: Some concerns about confounding, selection of the reported results; Funding: National Program on Basic Research Project of China, National Natural Science Foundation of China, Chinese Nutrition Society Nutrition Science Foundation
Tielemans, 2015 ^188^; PCS, Netherlands, Generation R Study; Analytic N=2748; - Age: ∼31.3y; - Race/Ethnicity (%): Dutch ancestry: 100; - Socioeconomic position:; ○ Education (%): Low and midlow: ∼18.2; High: ∼30.4; ○ Household income (%): <2200 Euro/mo: ∼28.3; - Pre-pregnancy BMI: ∼24.7; - Smoking (%): Until pregnancy known: ∼8.3; During pregnancy: ∼17.4; - DM/HDP (%):; ○ GDM: 11.0; ○ HDP: 7.4 | Vegetable, Oil and Fish DP, Nuts, High-Fiber Cereals and Soy DP, & Margarine, Sugar and Snacks DP (continuous alignment, quartiles of alignment); FFQ at: ∼13.4 GW; DP Descriptions:; - Vegetable, Oil and Fish DP: higher intake of vegetables, high fat dairy products, cereals (both low and high fiber), fish and shellfish, eggs and egg products, vegetable oils, coffee and tea, alcoholic beverages and legumes; - Nuts, High-Fiber Cereals and Soy DP: higher intake of potatoes and other tubers, fruits, high and low fat dairy products, high fiber cereals, meat and meat products, fish and shellfish, coffee and tea, sugar-containing beverages, light soft drinks, nuts, seeds and olives, and soy products; - Margarine, Sugar and Snacks DP: higher intake of potatoes and other tubers, high fat dairy products, low and high fiber cereals, meat and meat products, margarine and butter, sugar and confectionary and cakes, snacks, sugar-containing beverages, condiments and sauces, nuts, seeds and olives; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to maximum pregnancy weight; Self-reported pre-pregnancy weight collected at enrollment. Self-reported maximum pregnancy weight collected at 6wk postpartum. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Multinomial logistic regression; OR (95% CI); [underlined: Vegetable, Oil and Fish DP]; Per SD: p=0.21; Q2 vs. Q1 (Ref): 0.85 (0.60, 1.22), p=NS; Q3 vs. Q1 (Ref): 0.86 (0.60, 1.23), p=NS; Q4 vs. Q1 (Ref): 0.84 (0.58, 1.22), p=NS; [underlined: Nuts, High-Fiber Cereals and Soy DP]; Per SD: p=0.76; Q2 vs. Q1 (Ref): 0.77 (0.53, 1.13), p=NS; Q3 vs. Q1 (Ref): 0.86 (0.59, 1.25), p=NS; Q4 vs. Q1 (Ref): 0.85 (0.58, 1.24), p=NS; [underlined: Margarine, Sugar and Snacks DP]; Per SD: p=0.73; Q2 vs. Q1 (Ref): 0.97 (0.69, 1.36), p=NS; Q3 vs. Q1 (Ref): 0.93 (0.66, 1.32), p=NS; Q4 vs. Q1 (Ref): 0.98 (0.69, 1.40), p=NS; Excessive GWG; Multinomial logistic regression; OR (95% CI); [underlined: Vegetable, Oil and Fish DP]; Per SD: p=0.91; Q2 vs. Q1 (Ref): 1.08 (0.79, 1.48), p=NS; Q3 vs. Q1 (Ref): 1.05 (0.76, 1.46), p=NS; Q4 vs. Q1 (Ref): 1.06 (0.76, 1.48), p=NS; [underlined: Nuts, High-Fiber Cereals and Soy DP]; Per SD: p=0.46; Q2 vs. Q1 (Ref): 1.16 (0.82, 1.62), p=NS; Q3 vs. Q1 (Ref): 1.26 (0.89, 1.77), p=NS; Q4 vs. Q1 (Ref): 1.09 (0.77; 1.53), p=NS; [underlined: Margarine, Sugar and Snacks DP]; Per SD: p=0.09; Q2 vs. Q1 (Ref): 1.40 (1.04, 1.90), p<0.05; Q3 vs. Q1 (Ref): 1.37 (1.00, 1.87), p=NS; Q4 vs. Q1 (Ref):1.45 (1.06, 1.99), p<0.05 | Key confounders accounted for: Age, Race and/or ethnicity, Socioeconomic position, Pre-pregnancy BMI, Smoking, Parity; Key confounders not accounted for: Physical activity, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: Alcohol consumption during pregnancy, Stress during pregnancy, Fetal sex; Limitations: Issues with confounding, outcome measurement, and selection of the reported results; some concerns about exposure measurement, participant selection; Funding: Erasmus Medical Center; University Medical Centre Rotterdam; the Erasmus University, Rotterdam; the Dutch Ministry of Health, Welfare and Sport; the Netherlands Organization for Health Research and Development; Nestlé Nutrition; Metagenics Inc.
Wei, 2019 ^190^; PCS, China, BIGCS; Analytic N=5,733; - Age: ∼29.1y; - Socioeconomic position:; ○ Education (%): ≤High school: 8.0; Vocational/technical college: 23.6; Postgraduate: 12.9; ○ Income (%): ≤1500 Yuan/mo: 9.3; ≥9001 Yuan/mo: 16.9; - Pre-pregnancy BMI: 20.4± 2.6; - Smoking (%): 29.7 | Cereals DP, Vegetables DP, Meats DP, Fruits DP, Fish, beans, nuts, and yogurt DP, & Milk and milk powder DP (Cereals DP vs. all other DP); FFQ at: 24–27 GW; DP Descriptions:; - Cereals DP: Higher in cereals; - Vegetables DP: Higher in vegetables; - Meats DP: Higher in meats; - Fruits DP: Higher in fruits; - Fish, beans, nuts, and yogurt DP: Higher in fish, beans, nuts, and yogurt; - Milk and milk powder DP: Higher in milk and milk powder; Outcome and assessment methods:; GWG assessed at: Pre-pregnancy to delivery; Pre-pregnancy weight self-reported, weight before delivery measured at admission. GWG adequacy by 2009 IOM recommendations. | Inadequate GWG; Logistic regression; OR (95% CI); [underlined: Cereals:] Ref; [underlined: Vegetables:] 1.045 (0.835, 1.309), p=NS; [underlined: Meats:] 0.903 (0.713, 1.144), p=NS; [underlined: Fruits:] 0.904 (0.689, 1.187), p=NS; [underlined: Fish, beans, nuts, and yogurt:] 0.797 (0.638, 0.997), p<0.05; [underlined: Milk and milk powder:] 0.852 (0.664, 1.094), p=NS; Excessive GWG; Logistic regression; OR (95% CI); [underlined: Cereals:] Ref; [underlined: Vegetables:] 1.175 (0.954, 1.447), p=NS; [underlined: Meats:] 0.914 (0.733, 1.139), p=NS; [underlined: Fruits:] 1.393 (1.101, 1.763), p<0.05; [underlined: Fish, beans, nuts, and yogurt:] 1.094 (0.894, 1.338), p=NS; [underlined: Milk and milk powder:] 1.164 (0.932, 1.454), p=NS | Key confounders accounted for: Age, Socioeconomic position, Pre-pregnancy BMI, Parity; Key confounders not accounted for: Physical activity, Race and/or ethnicity, Smoking, DM in the current pregnancy, HDP in the current pregnancy; Other covariates: Gestational age at delivery; Limitations: Issues with confounding, exposure measurement, participant selection, missing data, and selection of the reported results; some concerns about deviations from intended exposures, outcome measurement; Funding: Guangzhou Science and Technology Bureau; National Natural Science Foundation of China
Reduced Rank Regression
Alves-Santos, 2018; PCS, Brazil, Municipal Health Centre Heitor Beltrão; Analytic N =173; - Age (y): 26.7±5.5; - Socioeconomic position:; ○ Per-capita family income (R$): 524.3±316.1; ○ Education (y): 8.6±2.9; - Pre-pregnancy BMI: 24.9±4.2; ○ (%): ≥25: 40.5; - DM/HDP (%):; ○ Blood glucose alterations during pregnancy: 0.0; ○ HOMA-IR: 1.2±0.8; - Smoking (%): 6.4 | Common-Brazilian DP & Western DP (tertiles of alignment); FFQ at: 30–36 GW; DP Descriptions:; - Common-Brazilian DP: Higher in beans; rice Lower in fast food and snacks; candies and table sugar; processed meats and bacon; - Western DP: Higher in fast food and snacks; processed meat and bacon; Lower in noodles, pasta, roots, and tubers; sodas; Outcome and assessment methods:; GWG assessed at: 5–13 GW to 38–40 GW; Weight measured by investigators. GWG: difference between weight at the last visit before delivery and the first study visit. GWG adequacy by 2009 IOM recommendations. | Excessive GWG; Logistic regression; OR (95% CI); [underlined: Common-Brazillian DP]; T2: 0.76 (0.33, 1.71); T1 (Ref), p=0.51; T3: 0.74 (0.32, 1.72); T1 (Ref), p=0.49; [underlined: Western DP]; T2: 1.37 (0.59, 3.18); T1 (Ref), p=0.46; T3: 1.33 (0.57, 3.11); T1 (Ref), p=0.50 | Key confounders accounted for: Pre-pregnancy BMI, Parity, DM in the current pregnancy; Key confounders not accounted for: Age, Physical activity, Race and/or ethnicity, Socioeconomic position, Smoking, HDP in the current pregnancy; Other covariates:; Limitations: Issues with confounding, exposure measurement, and participant selection; some concerns about selection of the reported results; Funding: The Carlos Chagas Filho Research Foundation from the State of Rio de Janeiro (FAPERJ)

a Abbreviations: AAPI: Asian American Pacific Islander; Adj Diff: adjusted difference; AHEI: alternative healthy eating index; AHEI-P: Alternate Healthy Eating Index for Pregnancy; aMED: alternate Mediterranean Diet Score; AWG: adequate weight gain; BIGCS: Born in Guangzhou Cohort Study; BMI: body mass index; CHDI-P: Chinese Healthy Diet Index for Pregnancy; CI: confidence interval; d: day(s); DASH: Dietary Approaches to Stop Hypertension; DII: Dietary inflammatory index; DM: diabetes mellitus; DP: dietary pattern; EDIP: Empirical Dietary Inflammatory Score; EGWG: excessive gestational weight gain; EVOO: extra virgin olive oil; EWG: excessive weight gain; FFQ: food frequency questionnaire; g: gram(s); GA: gestational age; GDM: gestational diabetes mellitus; GESTAFIT: GESTAtion and FITness; GW: gestational week(s); GWG: gestational weight gain; GWGR: rate of gestational weight gain; HDP: hypertensive disorders of pregnancy; HEI: healthy eating index; HELLP: Hemolysis, Elevated Liver enzymes and Low Platelets; hPDI: healthy plant-based diet index; hr: hour; HTN: hypertension; IOM: Institute of Medicine; IQR: interquartile range; IWG: insufficient weight gain; kcal: kilocalories; kg: kilogram(s); LMD: Lebanese Mediterranean Diet; MDQS: Maternal Diet Quality Score; Med: Mediterranean; MEDAS: Mediterranean diet adherence screener; mo: month; MoBa: Mothers and Babies cohort; MOMFIT: Maternal Offspring Metabolics Family Intervention Trial; MUFA: monounsaturated fatty acid; NFFD: Norwegian Fit for Delivery; NHB: non-Hispanic Black; NHLBI: National Heart, Lung, and Blood Institute; NHW: non-Hispanic White; NICHD: National Institute of Child Health and Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIEHS: National Institute of Environmental Health Sciences; NIFA: National institute of Food and Agriculture; NIH: National Institutes of Health; NINDS: National Institute of Neurological Disorders and Stroke; NND: New Nordic Diet; NR: not reported; NS: non-significant; NVP: nausea and vomiting in pregnancy; OR: odds ratio; PCS: prospective cohort study; PDI: plant-based diet index; PE: preeclampsia; PETALS: Pregnancy Environment and Lifestyle Study; PREWICE: PREgnant Women of Iceland; PRINCESA: Pregnancy Research on Inflammation; Nutrition and City Environments: Systematic Analyses; PUFA: polyunsaturated fatty acid; Q#: quartile; RCT: randomized controlled trial; Ref: reference; SD: standard deviation; SE: standard error; SECOST: Seremben Cohort Study; SEIFA IRSD: Socio-economic Index for Areas—Index of Relative Socio-economic Disadvantage; SEP: socioeconomic position; SFA: saturated fatty acid; svg: serving(s); T#: tertile; TEI: total energy intake; TM#: trimester; uPDI: unhealthy plant-based diet index; USDA: U.S. Department of Agriculture; wk: week(s); y: year(s)

Table 22 Risk of bias for randomized controlled trials examining dietary patterns consumed during pregnancy and gestational weight gain^a^

Article | Randomization | Deviations from intended interventions (effect of assignment) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Assaf-Balut, 2019^183^ | LOW | HIGH | LOW | LOW | HIGH | HIGH
Dodd, 2019^184^ | LOW | LOW | LOW | LOW | LOW | LOW
Van Horn, 2018^185^ | LOW | HIGH | LOW | LOW | LOW | HIGH

a Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2019 version)” ( Sterne JAC, Savović J, Page MJ, Elbers RG, Blencowe NS, Boutron I, Cates CJ, Cheng H-Y, Corbett MS, Eldridge SM, Hernán MA, Hopewell S, Hróbjartsson A, Junqueira DR, Jüni P, Kirkham JJ, Lasserson T, Li T, McAleenan A, Reeves BC, Shepperd S, Shrier I, Stewart LA, Tilling K, White IR, Whiting PF, Higgins JPT. RoB 2: a revised tool for asSEPsing risk of bias in randomised trials. BMJ 2019; 366: l4898.31462531

Table 23 Risk of bias for observational studies examining dietary patterns consumed during pregnancy and gestational weight gain (ROBINS-E)^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Acosta-Manzano, 2022^198^ | HIGH | LOW | HIGH | SOME CONCERNS | HIGH | LOW | SOME CONCERNS | HIGH
Alves-Santos, 2018^205^ | HIGH | VERY HIGH | HIGH | LOW | LOW | LOW | SOME CONCERNS | VERY HIGH
Augustin, 2020^212^ | HIGH | VERY HIGH | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | VERY HIGH
Berube, 2023^196^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | HIGH | LOW | LOW | SOME CONCERNS | HIGH
Cummings, 2022^203^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Hu, 2022^204^ | SOME CONCERNS | LOW | LOW | LOW | VERY HIGH | LOW | SOME CONCERNS | VERY HIGH
Itani, 2020^201^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Jarman, 2018^202^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Jayedi, 2023^199^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Li, 2021^194^ | SOME CONCERNS | LOW | LOW | LOW | LOW | LOW | SOME CONCERNS | SOME CONCERNS
Liu, 2023^195^ | SOME CONCERNS | LOW | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | SOME CONCERNS
Radwan, 2021^200^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | LOW | LOW | HIGH | HIGH
Silva-del Valle, 2013^206^ | HIGH | SOME CONCERNS | SOME CONCERNS | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Yang, 2022^197^ | HIGH | LOW | LOW | LOW | HIGH | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, moderate, serious, critical, or no information determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool (ROBINS-E Development Group ( Higgins J, Morgan R, Rooney A, Taylor K, Thayer K, Silva R, Lemeris C, Akl A, Arroyave W, Bateson T, Berkman N, Demers P, Forastiere F, Glenn B, Hróbjartsson A, Kirrane E, LaKind J, Luben T, Lunn R, McAleenan A, McGuinness L, Meerpohl J, Mehta S, Nachman R, Obbagy J, O'Connor A, Radke E, Savović J, Schubauer-Berigan M, Schwingl P, Schunemann H, Shea B, Steenland K, Stewart T, Straif K, Tilling K, Verbeek V, Vermeulen R, Viswanathan M, Zahm S, Sterne J). Risk Of Bias In Nonrandomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

Table 24 Risk of bias for observational studies examining dietary patterns consumed during pregnancy and gestational weight gain (RoB-NObs)^*^ * Possible ratings of low, moderate, serious, critical, or no information determined using the "Risk of Bias for Nutrition Observational Studies" tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

Article | Confounding | Classification of exposures | Selection of participants | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Ancira-Moreno, 2019^191^ | SERIOUS | SERIOUS | SERIOUS | LOW | MODERATE | MODERATE | SERIOUS
Hillesund, 2014^186^ | SERIOUS | MODERATE | SERIOUS | MODERATE | MODERATE | SERIOUS | SERIOUS
Hillesund, 2018^193^ | SERIOUS | SERIOUS | MODERATE | MODERATE | SERIOUS | MODERATE | SERIOUS
Hrolfsdottir, 2019^189^ | SERIOUS | MODERATE | MODERATE | LOW | SERIOUS | MODERATE | SERIOUS
Rifas-Shiman, 2009^187^ | SERIOUS | MODERATE | SERIOUS | MODERATE | SERIOUS | MODERATE | SERIOUS
Tielemans, 2015^188^ | SERIOUS | MODERATE | MODERATE | LOW | LOW | SERIOUS | SERIOUS
Wei, 2019^190^ | SERIOUS | SERIOUS | SERIOUS | NO INFORMATION | SERIOUS | MODERATE | SERIOUS
Yong, 2019^192^ | SERIOUS | MODERATE | SERIOUS | NO INFORMATION | NO INFORMATION | MODERATE | SERIOUS

## Dietary patterns during postpartum

### Description of the evidence

This systematic review included seven articles^198,203,207–212^ (one RCT and six PCS) that address the relationship between dietary patterns consumed during postpartum and postpartum weight change (PPWC). The search included articles from high and very high Human Development Index^*^ countries and the search time frame spanned between January 2000 and May 2023. Studies in this body of evidence included individuals during postpartum including those with overweight and obesity. Sample size in the included studies ranged between 102 to 1136 participants. Five of these seven studies were conducted in the U.S (all of which represented unique cohorts) ^203,207,209–211^ and the others were conducted in Spain^198^ and China.^208^

* The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990–2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

#### Participant characteristics

Age: Most of the participants were 20–35 years old, with one study conducted in China reporting that 14% of the participants were 35–45 years old.

Pre-pregnancy BMI: Three studies enrolled participants who had overweight/obesity,^209,211,203^ while two other studies reported that almost half of the participants had a pre-pregnancy BMI ≥25 kg/m^2^. Acosta-Manzano et al., reported a mean pre-pregnancy BMI of 23.7 kg/m^2^ ^198^ and Li et al., did not report pre-pregnancy BMI.^208^

Race and/or ethnicity: Studies conducted in the U.S., reported that ≥50% of participants were White; studies conducted in Spain and China did not report race and/or ethnicity information.

Socioeconomic position: The majority of participants in these studies had at least some college education. One study conducted in the U.S. reported that 35% of the participants were from low-income families,^207^ while another U.S., study noted that half of the participants had household income >$60,000.^211^

Smoking: Most studies reported that none or <10% of the participants were smokers. Notable exceptions were two studies that reported that 16–18% of the participants were former or current smokers.^203,207^

Gestational weight gain (GWG): Three studies noted that ~45-~60% of the participants reported excessive GWG.^203,207,209^ One study noted that GWG was ~15 kg and another study reported GWG of ~11 kg, until 33 weeks. Stendell-Hollis et al.,^210^ and Li et al.,^208^ did not report GWG of the participants.

Human milk feeding status: One trial exclusively enrolled participants who were lactating,^210^ while two other studies reported that about half of the participants were feeding human milk at baseline.^208,211^ One study reported a human milk feeding score^207^ and two others did not report on human milk feeding status.^198,203^

#### Intervention/exposure

In this body of evidence, dietary patterns were assessed using 1) index/score analysis, 2) factor/cluster analysis, and 3) an experimental diet. Below is the description of studies categorized by the methods used to measure the dietary patterns (Table 25).

Four articles used one or more of the following indices/scores:

- Mediterranean Diet Score^198^
- Alternate Mediterranean Diet Score (aMED), Alternative Healthy Eating Index-2010 (AHEI-2010)^207^
- HEI-2005^211^
- Nova ultra-processed^203^

Two articles assessed dietary patterns using factor/cluster analysis, which the authors labeled as:

- Plant food, Diverse, Traditional northern, Marine-flour^208^
- Junk food, Healthy food^209^

One trial was designed to assess the effects of a Mediterranean diet vs. USDA MyPyramid diet on PPWC.^210^

Table 25 List of dietary patterns consumed during postpartum that were examined in relation to postpartum weight change

Reference | Dietary pattern | Dietary components
Index/Score Analysis
Acosta- Manzano^198^ | Mediterranean Diet Score Index | Positive components^*^: fruits; vegetables; fish; * Positive and negative components, as indicated by the authors in the article.; Negative components^†^: red meat/subproducts; † Positive and negative components, as indicated by the authors in the article.; Unclear: whole-grain cereals; potatoes; pulses; olive oil; poultry; dairy products; Alcohol component excluded
Boghossian^207^ | aMED | Positive components: vegetables (excluding potatoes), legumes, fruit, nuts, whole grains, fish, ratio of monounsaturated fat to saturated fat; Negative components: red and processed meat
| AHEI-2010 | Positive components: vegetables (excluding potatoes), whole fruit, whole grains, nuts and legumes, % energy intake from PUFAs, long-chain (n-3) fats; Negative components: SSB and fruit juice, red and processed meat, % energy from trans-fat, sodium
Cummings^203^ | Nova | “Instant” foods; ready-to-heat pre-prepared pies, pasta, and pizza dishes; mass-produced packaged breads; reconstituted meats; sweet or savory packaged snacks; confectionery desserts; sweetened drinks
Wiltheiss^211^ | HEI-2005 | Positive components: total fruit, whole fruit, total vegetables, dark green and orange vegetables and legumes, total grains, whole grains, milk, meat and beans, oils; Negative components: saturated fat, sodium, calories from solid fats, alcoholic beverages, and added sugars
Factor/Cluster Analysis ^‡^; ‡ Author-derived dietary pattern
Li^208^ | Plant food | Higher intake of rice and vegetables
| Diverse | Higher intake of starchy roots, fruit, livestock meat, aquatic products
| Traditional northern | Higher intake of poultry, eggs, soup
| Marine-flour | Higher intake of flour, coarse food grains, marine fish
Østbye, 2012^209^ | Junk food | Higher intake of soda, sweetened drinks, French fries and chips, fast food
| Healthy food | Higher intake of milk, fruit, vegetables
Experimental diet
Stendell-Hollis^210^ | MED | Plant-based diet with whole grains, fresh fruits and vegetables, legumes and nuts, fish and poultry, olive oil, and low-fat dairy products, limited intake of red meat and processed meats/foods (≤2 servings/mo). Participants instructed to consume study-provided walnuts (28 g/d), 1–2 tbsp/d of olive oil, and ≥7 servings/d of fruits and vegetables. Participants encouraged to consume ≥6 servings/d of whole grains, ≥ 2 servings/d of fish per week, and to increase consumption of legumes while limiting the intake of whole fat dairy products, red meats, processed foods, desserts, and non-olive oil fat sources
| USDA MyPyramid | Emphasizes healthy eating choices. Intake of nuts, the use of olive oil, and an increase in fruits and vegetables were de-emphasized in order to differentiate from the MED diet

#### Outcomes

PPWC was assessed at different time points using different methods across the included studies:

- Stendell-Hollis et al.,^210^ assessed PPWC as the difference in weight measured by investigators at baseline (~17.5 wk postpartum) and follow-up (four mo after baseline).
- Acosta-Manzano et al.,^198^ assessed PPWC as the difference in pre-pregnancy weight (self-reported) and weight at six wk postpartum (assessed by the investigator).
- Boghossian et al.,^207^ assessed the difference between pre-pregnancy weight and weight at 21–34 wk, 35–48 wk, and 49–62 wk postpartum. All outcome measures were self-reported. The authors also assessed substantial PPWC, defined as weight ≥4.55 kg above pre-pregnancy weight, at multiple time-points during the postpartum period.
- Wiltheiss et al.,^211^ assessed PPWC as change in weight from ~five mo to ~15 mo postpartum and weight was measured by the investigators.
- Østbye et al.,^209^ reported PPWC as the weight change between baseline (six wk postpartum) and follow-up at 12 mo, 18 mo and 24 mo postpartum. Weight was measured by the investigators.
- Li et al.,^208^ defined PPWC as weight at 42 d (self-report) or six mo postpartum (investigator measured) minus pre-pregnancy weight (data record from antenatal examination).
- Cummings et al.,^203^ assessed PPWC as the change in weight between baseline (<12 weeks of pregnancy) and one year postpartum, both measured by the investigators. Percent of GWG retained was calculated by multiplying 100 by the difference in weight between the last prenatal medical visit (investigator measured) and one year postpartum (investigator measured), divided by GWG.

### Synthesis of the evidence

Table 27 presents the summary of the included studies and the risk of bias information are presented in Table 28 and Table 29. Overall, most studies did not show an association between dietary patterns consumed during postpartum and PPWC.

- Stendell-Hollis et al.^210^ compared the change in weight between participants randomized to two different diets: MED diet and the USDA MyPyramid diet. While both groups experienced a significant decrease in mean weight (kg) when compared to their respective baseline weight, the change in weight was not significantly different between the groups. This trial had a high risk of bias, primarily due to the deviation from intended intervention.
- Four PCS assessed dietary patterns using an index/score, (i.e., Med Diet score,^198^ aMED,^207^ AHEI-2010,^207^ HEI-2005^211^ and Nova ultra-processed^203^) none of which were associated with PPWC. In addition, Cummings et al.,^203^ assessed percent GWG retained, which was also not associated with the Nova ultra-processed dietary pattern. All four studies had a high risk of bias because of concerns with confounding and missing data.
- Li et al.^208^ showed that the “Plant food” dietary pattern was associated with greater PPWC at 42 d postpartum, but not at six mo postpartum. On the other hand, the “Diverse” dietary pattern was associated with lower PPWC at six mo only. There were no associations between the “Traditional northern” and “Marine-flour” dietary patterns and PPWC at 42 d or six mo postpartum. This study had a very high risk of bias because of concerns with confounding, missing data, exposure and outcome measurements.
- Østbye et al.^209^ noted that the “Junk food” dietary pattern was associated with greater PPWC at 12, 18 and 24 mo postpartum, whereas the “Healthy food” dietary pattern was not associated with PPWC at any of these time points. Østbye et al. had a high risk of bias because of missing data and selection of reported results.

The lack of association between dietary patterns during postpartum and postpartum weight change in this body of evidence may be due to methodological limitations, as noted by high or very high risk of bias in all the studies. Specifically, many observational studies had issues with confounding and missing data. The RCT also had issues with deviation from the intended intervention. There was considerable heterogeneity in the dietary patterns which limited the ability to compare patterns across studies in the body of evidence. Further, there were differences in outcome assessment, including the number of measurements, the duration of follow-up, and whether the outcome was self-reported or investigator measured. There were concerns with precision, with only one trial being included which also had notable limitations. Further, studies were not entirely generalizable since they did not reflect the diversity of the U.S. population. This body of evidence included both large and small studies with significant as well as null findings, so publication bias may have been less likely.

### Conclusion statement and grade

The 2025 Dietary Guidelines Advisory Committee developed a conclusion statement to answer the question, “What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?” based on their review of the body of evidence examining dietary patterns consumed during postpartum and postpartum weight change. (Table 26).

Table 26 Conclusion statement, grades for dietary patterns during postpartum and postpartum weight change

Conclusion Statement | A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during postpartum and postpartum weight change because there are substantial concerns with consistency, precision, risk of bias and generalizability in the body of evidence.
Grade | Grade not assignable
Body of Evidence | 7 articles: 1 RCT and 6 PCS
Rationale | The available evidence was too inconsistent to draw meaningful conclusions on the relationship between dietary patterns consumed during postpartum and postpartum weight change (PPWC). There was considerable heterogeneity in the dietary patterns, timing, and methodology of PPWC assessment. All studies had high or very high risk of bias. There were issues with precision, with only one trial being included which had notable limitations. Further, studies were not entirely generalizable since they did not reflect the diversity of the U.S. population.

Table 27 Evidence examining the relationship between dietary patterns consumed during postpartum and postpartum weight change^a^

Study Characteristics | Intervention or Exposure and Outcome | Results | Confounding and Funding
RCT
Index/Score
Stendell-Hollis, 2013 ^210^; RCT, Parallel-arm, United States, University of Arizona; Baseline N=129; Analytic N=102 (Attrition: ∼21%); - Age (y): 29.7±4.6; - Race/Ethnicity (%): Hispanic or Latino: 24.8; NHW: 75.2; - Socioeconomic position:; ○ Education (%): College degree: 69.0; - Pre-pregnancy BMI: 25.5± 4.7; ○ ≥25 (%): 49.6; ○ Baseline BMI: 27.2±4.9; - Smoking (%): 0.0; - Human milk feeding status: ≥3 times/d for 6 mo after recruitment; ○ Formula supplementation use: 26.8% | Mediterranean-Style (MED) vs USDA MyPyramid Diet; FFQ at: Baseline (∼17.5 wk postpartum); Follow-up (4 mo after baseline); Dietary pattern description:; - MED: Plant-based diet with whole grains, fresh fruits and vegetables, legumes and nuts, fish and poultry, olive oil, and low-fat dairy products, limited intake of red meat and processed meats/foods (≤2 servings/mo). Participants instructed to consume study-provided walnuts (28 g/d), 1–2 tbsp/d of olive oil, and ≥7 servings/d of fruits and vegetables. Participants encouraged to consume ≥6 servings/d of whole grains, ≥2 servings/d of fish per week, and to increase consumption of legumes while limiting the intake of whole fat dairy products, red meats, processed foods, desserts, and non-olive oil fat sources; - USDA MyPyramid Diet: Emphasized healthy eating choices. Intake of nuts, the use of olive oil, and an increase in fruits and vegetables were de-emphasized in order to differentiate from the MED diet; Total MED diet score differed between groups at follow-up; Outcome and assessment methods:; PPWC assessed at: Baseline (∼17.5 wk postpartum) to follow-up (4 mo after baseline). Weight measured by investigators. | Postpartum weight change:; Mann-Whitney U-test; Mean diff, kg; MED: −2.31±3.42; USDA: −3.11±3.35; p=0.581 | Limitations: Issues with deviation from intended intervention and some concerns with selection of the reported results; Funding: California Walnut Commission; Nutritional Sciences Department at the University of Arizona; USDA
Cohort Studies
Index/Score
Acosta-Manzano, 2022 ^198^; PCS, Spain, GESTAFIT; Analytic N =114; - Age (y): 33±5; - Socioeconomic position:; ○ Education (%): <University: 36.4; University degree: 63.6; - Pre-pregnancy BMI: 23.7±3.9; - GWG (kg): Prepregnancy to Week 33: 10.8±4.9; - Smoking: Cigarettes/d (Median (IQR)): 0 (0, 0) | Mediterranean Diet Score (continuous); FFQ at: 6 wk postpartum; Dietary pattern description:; - Positive components: fruits; vegetables; fish; - Negative components: red meat/subproducts; - Unclear: whole-grain cereals; potatoes; pulses; olive oil; poultry; dairy products; Outcome and assessment methods:; PPWC assessed at: Pre-pregnancy to 6 wk postpartum Pre-pregnancy weight self-reported. Postpartum weight measured by investigators. | Postpartum weight change; Linear regression; β (SE), kg; 0.01 (0.12), p=0.91; Adj R^2^=0.03; TEI adjustment: p=0.93 | Key confounders accounted for: Smoking status, Physical activity, Pre-pregnancy BMI and/or GWG; Key confounders not accounted for: Parity, Race and/or Ethnicity, Maternal age, Socioeconomic Position, Human milk feeding status; Other covariates: Weeks between birth and postpartum assessment, in-bed time, sleep (duration, awakening time after onset, efficiency, quality), upper body muscle strength, cardiorespiratory fitness; Limitations: Issues with confounding, selection of participants and missing data and some concerns with selection of the reported results; Funding: University of Granada, the Spanish Ministry of Economy and Competitiveness, the Spanish Ministry of Education, Culture and Sports, Instituto de Salud Carlos III, European Social Fund
Boghossian, 2013 ^207^; PCS, United States, IFPS II; Analytic N =1136; - Age (y): aMED T1: 28.4±5.2; aMED T3: 30.2±5.4, p<0.001; - Race/Ethnicity (%): NHW: 86.0; NHB: 3.5; Hispanic: 5.2; AAPI/Other: 5.4; - Socioeconomic position:; ○ Education (%): aMED T1: ≤High school: 23.0; Graduate degree: 8.5; aMED T3: ≤High school: 12.7; Graduate degree: 14.4, p<0.001; ○ Poverty level (<185% of federal poverty) (%): aMED T1: 40.4; aMED T3: 31.3, p=0.012; - Pre-pregnancy BMI: (%): <25: 52.7; ≥30: 22.2; - GWG (%): Inadequate: 18.1; Adequate: 36.9; Excessive: 45.1; - Smoking (%): aMED T1: 25.2; aMED T3: 7.1, p<0.001; - HMF status: HMF score (≤1y postpartum: 1 pt/wk exclusive HMF, 0.5 pt/wk partial HMF; >1y postpartum: 0.25 pt/wk any BF) 11–20 wk: aMED T1: 5.8±4.7; aMED T3: 8.3±4.7, p<0.001 21–34 wk: aMED T1: 9.4±8.5; aMED T3: 14.9±8.4, p<0.001 35–48 wk: aMED T1: 11.6±10.8; aMED T3: 18.0±11.1, p<0.001 49–62 wk: aMED T1: 13.4±13.0; aMED T3: 21.1±13.7, p<0.001 | aMED (categorical tertiles of adherence); FFQ at: ∼4 mo postpartum; Dietary pattern description:; - Positive components: vegetables (excluding potatoes), legumes, fruit, nuts, whole grains, fish, ratio of monounsaturated fat to saturated fat; - Negative components: red and processed meat; Outcome and assessment methods:; Total PPWC and substantial PPWC assessed at: Pre-pregnancy to 21–34 wk, to 35–48 wk, and to 49–62 wk postpartum; All weight measures self-reported. Total PPWC defined as difference between pre-pregnancy weight and weight at each follow-up time point. Substantial PPWC defined as ≥4.55 kg above pre-pregnancy weight. | Total Postpartum weight change; Linear mixed model; Mean diff (95% CI), kg; T2 vs. T1: 0.41 (−0.49, 1.30), p=0.37; T3 vs. T1: −0.26 (−1.36, 0.84), p=0.65; Substantial Postpartum weight change; Generalized estimating equations; OR (95% CI); T2 vs. T1: 1.14 (0.84, 1.57), p=0.40; T3 vs. T1: 1.09 (0.74, 1.60), p=0.68 | Key confounders accounted for: Smoking status, Race and/or Ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI and/or GWG, Human milk feeding status; Key confounders not accounted for: Physical activity; Other covariates: Postpartum time, marital status, TEI, Parity; Limitations: Issues with missing data and some concerns with confounding, selection of participants, outcome measurements and selection of reported result
| AHEI-2010 (continuous tertiles of adherence); FFQ at: ∼4 mo postpartum; Dietary pattern description:; - Positive components: vegetables (excluding potatoes), whole fruit, whole grains, nuts and legumes, % energy intake from PUFAs, long-chain (n-3) fats; - Negative components: SSB and fruit juice, red and processed meat, % energy from trans-fat, sodium; Outcome and assessment methods:; Total PPWC and substantial PPWC assessed at: Pre-pregnancy to 21–34 wk, to 35–48 wk, and to 49–62 wk postpartum; All weight measures self-reported. Total PPWC defined as difference between pre-pregnancy weight and weight at each follow-up time point. Substantial PPWC defined as ≥4.55 kg above pre-pregnancy weight. | Total Postpartum weight change; Linear mixed model; Mean diff (95% CI), kg; T2 vs. T1: 0.24 (20.70, 1.18), p=0.62; T3 vs. T1: 0.64 (20.34, 1.61), p=0.20; Substantial Postpartum weight change; Generalized estimating equations; OR (95% CI); T2 vs. T1: 0.99 (0.73, 1.33), p=0.94; T3 vs. T1: 1.28 (0.94, 1.74), p=0.12 | Key confounders accounted for: Smoking status, Age, Socioeconomic position, Pre-pregnancy BMI and/or GWG, HMF status; Key confounders not accounted for: Physical activity; Other covariates: Postpartum time, marital status, TEI; Limitations: Issues with missing data and some concerns with confounding, selection of participants, outcome measurements and selection of reported result; Funding: NIH; FDA; CDC
Cummings, 2022 ^203^; PCS, United States, PEAS; Analytic N=321; - Age (y): 30.5±4.7; - Race/Ethnicity (%): White: 71; Black: 17, Asian: 5, Other or multiracial: 6; Hispanic: 9; - Socioeconomic position:; ○ Income-Poverty Ratio: 3.84±1.97; ○ Education (%): College degree: 72; - Pre-pregnancy BMI (%): <18.5: 0.0; ≥25: 25.1; >30: 27.1; - GWG (%): Inadequate: 19; Adequate: 34; Excessive: 47; - Smoking (%): Current: 2; Former: 18 | Nova * (continuous adherence, % energy intake z-scored); * Not an abbreviation; ASA24 at: ∼2mo, 6mo, 1y postpartum; Dietary pattern description:; - Positive components: ‘instant’ foods; ready-to-heat pre-prepared pies, pasta, and pizza dishes; mass-produced packaged breads; reconstituted meats; sweet or savory packaged snacks; confectionery desserts; sweetened drinks; Outcome and assessment methods:; PPWR, PPWC assessed at ∼1y postpartum; PPWR (%) calculated as difference in weight from last prenatal medical visit to 1y postpartum divided by GWG, multiplied by 100.; PPWC (kg) calculated by subtracting weight at baseline (<12 gW) from weight at 1y postpartum.; Weight, height measured by investigators, and from prenatal medical records. | Postpartum weight retention; Linear regression, % per-SD UPF during postpartum; β±SE (95% CI); −4.33±3.39 (−11, 2.34), p=0.202; Postpartum weight change; Linear regression, kg per-SD UPF during postpartum; β±SE (95% CI); −0.44±0.36 (−1.14, 0.27), p=0.222 | Key confounders accounted for: Age, Physical activity, Pre-pregnancy BMI and/or GWG (PPWR only), Socioeconomic position, Smoking status; Key confounders not accounted for: Race and/or /Ethnicity, Parity, Human milk feeding status; Other covariates: TEI, time; Limitations: Issues with confounding and some concerns with exposure measurement, missing data and selection of reported result; Funding: NICHD, NIH
Wiltheiss, 2013 ^211^; PCS, United States, KAN-DO; Analytic N =276; - Age (y): CG: 33.7±4.3; IG: 33.3±4.6; - Race/Ethnicity (%): White/Other: CG: 83; IG: 84; Black: CG: 17; IG: 16; - Socioeconomic position:; ○ Household Income (%): ≤$15,000: CG: 6; IG: 6; ≥$60,000: CG: 64; IG: 60; ○ Education (%): ≤12th grade: CG: 9; IG: 7; Graduate school: CG: 28; IG: 33; ○ Employment (%): Full time: CG: 30; IG: 29; Part time: CG: 21; IG: 18; Not paid for work: CG: 49; IG: 53; - Pre-pregnancy BMI: ≥25: 100%; ○ Pre-pregnancy weight (kg): CG: 82.7±13.1; IG: 81.7±15.5; - GWG (kg): CG: 14.4±5.8; IG: 14.9±6.8; - Smoking (%): CG: 3.0; IG: 5.0; - HMF status (%): Exclusive HMF: CG: 50; IG: 44; Mixed feeding: CG: 14; IG: 20; Exclusive FF: CG: 36; IG: 36 | HEI-2005 (continuous adherence); 24 hr Recall at: ∼5 mo postpartum (range: 2–7 mo postpartum); Dietary pattern description:; - Positive components: total fruit, whole fruit, total vegetables, dark green and orange vegetables and legumes, total grains, whole grains, milk, meat and beans, oils; - Negative components: saturated fat, sodium, calories from solid fats, alcoholic beverages, and added sugars; Outcome and assessment methods:; PPWC assessed at: ∼5 mo postpartum to ∼15 mo postpartum; Weight measured by investigators. | Postpartum weight change; Multivariate regression, kg; p=0.07 | Key confounders accounted for: Smoking status, Race and/or Ethnicity, Age, Socioeconomic position, Pre-pregnancy BMI and/or GWG, HMF status; Key confounders not accounted for: Physical activity; Other covariates: Trial arm assignment, Marital status, Depression, TEI, Parity; Limitations: Some concerns with confounding, exposure measurement, selection of participants, missing data and selection of the reported results; Funding: NIDDK, NIH
Factor/Cluster Analysis
Li, 2020 ^208^; PCS, China, MICS; Analytic N =504; - Age (y): (%): 21–29: 43.3; 30–34: 42.1; 35–45: 14.5; - Socioeconomic position:; ○ Education (%): ≤High school: 19.7; ≥Bachelor’s: 60.6; ○ Family income per capita (%): ≤3,000 yuan/mo: 21.7; ≥6,000 yuan/mo: 37.3; - HMF status (%): HMF: 48.7; Mixed feeding: 51.3 | Plant food DP, Diverse DP, Traditional northern DP, & Marine-flour DP (continuous adherence); FFQ at: 0–3 mo or 6–8 mo postpartum, recalling diet at 1 mo postpartum; Dietary pattern description:; - Plant food DP: Higher intake of rice and vegetables; - Diverse DP: Higher intake of starchy roots, fruit, livestock meat, aquatic products; - Traditional northern DP: Higher intake of poultry, eggs, soup; - Marine-flour DP: Higher intake of flour, coarse food grains, marine fish; Outcome and assessment methods:; PPWC assessed at: Pre-pregnancy to 42 d and to 6 mo postpartum; Pre-pregnancy weight taken from antenatal records. Weight at 42 d postpartum recalled by participants at 0–3 mo or 6–8 mo. Weight at 6 mo measured by investigators. PPWC calculated as weight at 42 d or 6 mo postpartum minus pre-pregnancy weight. | Postpartum weight change at 42 d; Linear regression; β (95% CI), kg; [underlined: Plant food DP]: 0.11 (0.15, 0.80), p=0.004; [underlined: Diverse DP]: −0.05 (−0.56, 0.10), p=0.18; [underlined: Traditional northern DP]: −0.004 (−0.34, 0.31), p=0.92; [underlined: Marine-flour DP]: 0.07 (−0.02, 0.66), p=0.06; Postpartum weight change at 6 mo; Linear regression; β (95% CI), kg; [underlined: Plant food DP]: 0.09 (−0.14, 1.14), p=0.12; [underlined: Diverse DP]: −0.14 (−2.21, −0.21), p=0.02; [underlined: Traditional northern DP]: −0.11 (−1.38, 0.01), p=0.054; [underlined: Marine-flour DP]: −0.05 (−0.97, 0.36), p=0.37 | Key confounders accounted for: Age, Socioeconomic position, Pre-pregnancy BMI and/or GWG, Human milk feeding status; Key confounders not accounted for: Parity, Smoking status, Race and/or Ethnicity, Physical activity; Other covariates: Delivery mode, puerperal caregiver, professional dietary counselling; Limitations: Issues with confounding, missing data, exposure and outcomes measurements and some concerns with selection of participants and selection of the reported results; Funding: No external funding
Østbye, 2012 ^209^; PCS, United States, AMP; Analytic N =348; - Age (y): 30.9±5.6; - Race/Ethnicity (%): White: 52.7; Black: 45.1; Other: 2.2; - Socioeconomic position: Education (%): ≤High school: 20.7; ≥College degree: 54.9; - Pre-pregnancy BMI: ≥25: 100%; ○ Baseline BMI: 33.0±6.4 (%): 25–29.9: 40.0; ≥40: 13.1; - GWG (kg): 14.9±8.7 (%): Inadequate: 19.6; Excessive: 59.6; - Smoking (%): ∼5.8; - Human milk feeding status: HMF score (0 pt/mo exclusive FF, 1 pt/mo mixed feeding, 2 pt/mo exclusive HMF) at 12 mo postpartum: 8.2±8.7; ○ 0: 33.8%; 18–14: 19.1% | Junk food DP & Healthy food DP (continuous adherence); FFQ at: 6 wk, 12 mo, 18 mo, and 24 mo postpartum; Dietary pattern description:; - Junk food DP: Higher intake of soda, sweetened drinks, french fries and chips, fast food; - Healthy food DP: Higher intake of milk, fruit, vegetables; Outcome and assessment methods:; PPWC assessed at: 6 wk to 12 mo, 18 mo, and 24 mo postpartum; Weight measured by investigators. PPWC defined as weight change from baseline to each follow-up time point. | Postpartum weight change at 12 mo; Repeated measures mixed model; β (SE), kg per 1 SD score increase; [underlined: Junk food DP]: 0.90 (0.4), p<0.05; [underlined: Healthy food DP]: 0.02 (0.4), p>0.05; Postpartum weight change at 18 mo; Repeated measures mixed model; β (SE), kg per 1 SD score increase; [underlined: Junk food DP]: 1.20 (0.4), p<0.01; [underlined: Healthy food DP]: −0.35 (0.4), p>0.05; Postpartum weight change at 24 mo; Repeated measures mixed model; β (SE), kg per 1 SD score increase; [underlined: Junk food DP]: 1.34 (0.4), p<0.01; [underlined: Healthy food DP]: −0.36 (0.3), p>0.05; Sensitivity analysis excluding all participants who became pregnant again during follow-up were very similar (Data NR) | Key confounders accounted for: Race and/or ethnicity, Age, Socioeconomic position, Physical activity, Pre-pregnancy BMI and/or GWG, Human milk feeding status; Key confounders not accounted for: Smoking status; Other covariates: Marital status, Pregnancy since baseline, Trial arm assignment, Hormonal contraception, Parity; Limitations: Issues with missing data and selection of the reported results; Funding: NIDDK, NIH

a Abbreviations: AAPI: Asian American Pacific Islander; adj: adjusted; aMED: alternate Mediterranean Diet Score; AMP: Active Mothers Postpartum; BMI: body mass index; CG: control group; d: day(s); DP: dietary pattern; FF: formula feeding; FFQ: food frequency questionnaire; GESTAFIT: GWG: gestational weight gain; HEI: Healthy Eating Index; HMF: human milk feeding; hr: hour; IFPS: Infant Feeding Practices Study; IG: intervention group; IQR: interquartile range; KAN-DO: Kids and Adults Now - Defeat Obesity; kg: kilogram(s); MICS: Mother-Infant Cohort Study; mo: month(s); NHB: non-Hispanic Black; NHW: non-Hispanic White; NICHD: Eunice Kennedy Shriver National Institute of Child Health and Human Development; NIDDK: National Institute of Diabetes and Digestive and Kidney Diseases; NIH: National Institutes of Health; NR: not reported; OR: odds ratio; PCS: prospective cohort study; PPWC: postpartum weight change; PPWR: postpartum weight retention; pt: point(s); RCT: randomized controlled trial; SD: standard deviation; SE: standard error; T#: tertile; TEI: total energy intake; wk: week(s); y: year(s)

Table 28 Risk of bias for randomized controlled trials examining dietary patterns consumed during postpartum and postpartum weight change ^b^

Article | Randomization | Deviations from intended interventions (effect of assignment or per-protocol) | Missing outcome data | Outcome measurement | Selection of the reported result | Overall risk of bias
Stendell-Hollis, 2013^210^ | LOW | HIGH | LOW | LOW | SOME CONCERNS | HIGH

b Possible ratings of low, some concerns, or high determined using the "Cochrane Risk-of-bias 2.0" (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 29 Risk of bias for observational studies examining dietary patterns consumed during postpartum and postpartum weight change^a^

Article | Confounding | Exposure measurement | Selection of participants | Post-exposure interventions | Missing data | Outcome measurement | Selection of the reported result | Overall risk of bias
Acosta-Manzano, 2022^198^ | HIGH | LOW | HIGH | LOW | HIGH | LOW | SOME CONCERNS | HIGH
Boghossian, 2013^207^ | SOME CONCERNS | LOW | SOME CONCERNS | LOW | HIGH | SOME CONCERNS | SOME CONCERNS | HIGH
Li, 2020^208^ | HIGH | HIGH | SOME CONCERNS | LOW | HIGH | HIGH | SOME CONCERNS | VERY HIGH
Østbye, 2012^209^ | SOME CONCERNS | LOW | LOW | LOW | HIGH | LOW | HIGH | HIGH
Wiltheiss, 2013^211^ | SOME CONCERNS | SOME CONCERNS | SOME CONCERNS | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH
Cummings, 2022^203^ | HIGH | SOME CONCERNS | LOW | LOW | SOME CONCERNS | LOW | SOME CONCERNS | HIGH

a Possible ratings of low, some concerns, high, very high, not applicable, or no information were determined using the "Risk of Bias in Non-randomized Studies of Exposures (ROBINS-E)" tool (ROBINS-E Development Group ( Higgins J, Morgan R, Rooney A, . Risk Of Bias In Non-randomized Studies - of Exposure (ROBINS-E). Launch version, 1 June 2022. Available from: https://www.riskofbias.info/welcome/robins-e-tool. ) *Low risk of bias except for concerns about uncontrolled confounding.

## Summary of conclusion statements and grades

The 2025 Dietary Guidelines Advisory Committee answered the systematic review question, “What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?”, with the following conclusion statement[s].^*^The grades reflect the strength of the evidence underlying the conclusion statements.

* A conclusion statement is carefully constructed, based on the evidence reviewed, to answer the systematic review question. A conclusion statement does not draw implications and should not be interpreted as dietary guidance.

#### Infants and young children up to age 24 months

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by infants and young children up to age 24 months and growth, body composition, and risk of obesity because of substantial concerns with consistency. (Grade: Grade Not Assignable)

#### Children and adolescents

- Dietary patterns consumed by children and adolescents that are characterized by higher intakes of vegetables, fruit, legumes, nuts, whole grains, fish/seafood, dairy (low-fat, unsweetened) and lower intakes of red and processed meats, sugar-sweetened beverages, and sugar-sweetened or savory/salty snack foods are associated with favorable growth patterns, and lower adiposity and risk of obesity later in childhood and early adulthood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- Dietary patterns consumed by children and adolescents that are characterized by higher intakes of red and processed meats, refined grains, fried potatoes, sugar-sweetened beverages, and sugar-sweetened or savory/salty snack foods and lower intakes of vegetables, fruit, and whole grains are associated with unfavorable growth patterns, and higher adiposity and risk of obesity later in childhood and early adulthood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

#### Adults and older adults

- Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish/seafood; and lower intakes of meats (including red and processed meats), refined grains and sugar-sweetened foods and beverages are associated with lower adiposity (body fat, body weight, BMI, and/or waist circumference) and lower risk of obesity. These dietary patterns also included higher intakes of unsaturated fats and lower intakes of saturated fats and sodium. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

#### Pregnancy

- Dietary patterns consumed during pregnancy may be associated with a lower risk of excessive gestational weight gain. These patterns tend to emphasize higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish and dairy and lower intakes of added sugars. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of inadequate gestational weight gain because there are substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

#### Postpartum

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during postpartum and postpartum weight change because there are substantial concerns with consistency, precision, risk of bias and generalizability in the body of evidence in the body of evidence. (Grade Not Assignable)

## Research recommendations

- Conduct repeat measures of dietary patterns using validated dietary assessment tools and methods, preferably at multiple times throughout the entire course of follow-up and provide better description of the foods and/or components consumed as part of the dietary pattern while consistently incorporating diet quality. Studies examining dietary patterns based on a single diet assessment (often at baseline only) and outcome measure do not capture changes in dietary intake and outcomes over time.
- For children under the age of 2 years, create consistency across research in terms of analytical methods used to derive, assign, and examine dietary patterns consumed from birth to 12 months, and 12 to 24 months of age that include human milk and/or infant formula.
  ○ Use valid dietary assessment methods (i.e., 24-hour recalls) and apply tools consistently to identify dietary patterns, such as Toddlers HEI-2020, in relation to health outcomes to more comprehensively inform the development of dietary recommendations.
  ○ Provide greater specificity when describing the components such as ‘commercial baby food’, ‘baby snacks’, and ‘textured foods’, that often comprise dietary patterns unique to this life stage.
- Examine dietary patterns consumed earlier in childhood, preferably during ages 2 to 5 years, in relation to changes in growth patterns, body composition, and risk of obesity later in childhood through adolescence and early adulthood. Limited studies are available that administer dietary assessments in infants and young children up to age 24 months, adolescents, older adults, and individuals during pregnancy and postpartum.
- Conduct well-controlled, randomized interventions, particularly in the United States with diverse populations, to examine the effect of dietary patterns consumed in early childhood (e.g., 2 to 5 years) throughout adolescence and growth, body composition, and risk of obesity outcomes across the lifespan.
- Conduct well-controlled, randomized interventions, particularly in the United States with diverse populations, to examine the effect of dietary patterns consumed, particularly in younger adults ages 19 to 65 years, and body composition, and risk of obesity later in adulthood.
- Collect outcome measures objectively for growth, body composition, and risk of obesity [e.g., PEAPOD] and use consistent cut-off standards. Studies that rely on self-report of outcome measures and do not apply standard cut-offs to capture growth, body composition, and risk of obesity pose higher risk of bias due to outcome measurement error and may limit the comparability across findings.
- For studies including individuals who are pregnant,
  - collect data on weight multiple times during pregnancy to better understand their longitudinal associations, rather than one-time measurements. It is ideal to include weight change measurements that are assessed by the investigator, rather than self-reported.
  - assess weight change from earlier in pregnancy or preferably pre-pregnancy, rather than from mid- or late-pregnancy
  - administer dietary assessments as early as possible in pregnancy and use assessment methods that have been validated in pregnant populations.
- Collect detailed lifestyle information, especially physical activity, particularly in observational studies
- Control for confounding factors that impact the relationship between dietary patterns and growth, body composition, and risk of obesity, particularly with respect to:
  ○ total energy intake and the role it plays, such as why and how total energy intake was controlled for while considering developmental stage/level relative to growth.
  ○ race and/or ethnicity of participants
  ○ anthropometry at baseline
- Consider effect modification or mediating factors, including social determinants of health such as food insecurity status and socioeconomic position of participants.
- Include diverse populations with varying distributions of race and/or ethnicity and/or socioeconomic background, report the distribution of these factors, as well as how or if these factors may impact results. Studies that do not provide these details limit the ability to determine generalizability across findings.
- Take systems-level approaches to examining dietary patterns consumed and changes in growth, body composition, and risk of obesity to better understand other contextual and environmental factors impacting these relationships synergistically.