# Plain-language summary

### What is the question?

The question is: What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity? The population of interest included infants and young children up to age 24 months, children and adolescents, adults and older adults, individuals during pregnancy, and individuals during postpartum.

### Why was this question asked?

This systematic review was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025-2030.

### How was this question answered?

The Committee conducted a systematic review to answer this question with support from the USDA Nutrition Evidence Systematic Review team. This review updated existing reviews that were conducted by the 2020 Dietary Guidelines Advisory Committee, and as part of the Pregnancy and Birth to 24 Months Project and Dietary Patterns Systematic Reviews Project.

### What is the answer to the question?

#### Infants and Young Children up to age 24 months

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed by infants and young children up to age 24 months and growth, body composition, and risk of obesity because of substantial concerns with consistency. (Grade: Grade Not Assignable)

#### Children and Adolescents

- Dietary patterns consumed by children and adolescents that are characterized by higher intakes of vegetables, fruit, legumes, nuts, whole grains, fish/seafood, and dairy (low-fat, unsweetened) and lower intakes of red and processed meats, sugar-sweetened beverages, and sugar-sweetened or savory/salty snack foods are associated with favorable growth patterns, lower adiposity, and lower risk of obesity later in childhood up to early adulthood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- Dietary patterns consumed by children and adolescents that are characterized by higher intakes of red and processed meats, refined grains, sugar-sweetened beverages, sugar-sweetened or savory/salty snack foods, and fried potatoes and lower intakes of vegetables, fruit, and whole grains are associated with unfavorable growth patterns, higher adiposity, and higher risk of obesity later in childhood and adulthood. This conclusion statement is based on evidence graded as limited. (Grade: Limited)

#### Adults and Older Adults

- Dietary patterns consumed by adults and older adults that are characterized by higher intakes of vegetables, fruits, legumes, nuts, whole grains, and fish/seafood and lower intakes of meats (including red and processed meats), refined grains and sugar-sweetened foods and beverages are associated with lower adiposity (body fat, body weight, BMI, and/or waist circumference) and lower risk of obesity. These dietary patterns also included higher intakes of unsaturated fats and lower intakes of saturated fats and sodium. This conclusion statement is based on evidence graded as moderate. (Grade: Moderate)

#### Pregnancy

- Dietary patterns consumed during pregnancy may be associated with a lower risk of excessive gestational weight gain. These patterns tend to emphasize higher intakes of vegetables, fruits, legumes, nuts, whole grains, fish and dairy and lower intakes of added sugars. This conclusion statement is based on evidence graded as limited. (Grade: Limited)
- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during pregnancy and risk of inadequate gestational weight gain because there are substantial concerns with consistency in the body of evidence. (Grade: Grade Not Assignable)

#### Postpartum

- A conclusion statement cannot be drawn about the relationship between dietary patterns consumed during postpartum and postpartum weight change because there are substantial concerns with consistency, precision, risk of bias and generalizability in the body of evidence. (Grade Not Assignable)

### How up-to-date is this systematic review?

Conclusion statements from this review are based on studies published between January 1980 and May 2023.