# Appendix 6 Dietary pattern visualization

The Committee’s synthesis was facilitated by data visualization tables that presented the dietary pattern components in each of the dietary patterns examined in the body of evidence. During evidence synthesis, these tables were used in conjunction with other materials to compare and contrast the components between and within the dietary patterns studied along with the direction, magnitude, and statistical significance of reported results. Detailed information about the body of evidence, including study and population characteristics, reported results for all relevant outcomes, key confounders accounted for, study limitations, and funding sources, are summarized in the evidence tables of this report (Table 10; Table 14; Table 16).

Each column represents the most commonly reported foods/food groups or nutrients across dietary patterns in this body of evidence. Two additional columns, “Other, A” and “Other, B”, captured a variety of other components less frequently reported across dietary patterns that did not fit into one of the preceding columns or categories, such as fast food, ready-to-eat dishes, pizza, and chocolate. Multiple symbols in each cell mean that the dietary pattern included multiple components from that column/category. Empty cells mean that the dietary pattern did not describe a component within that column/category.

## Children and adolescents

Table A 9 Visualization of dietary pattern components across dietary patterns consumed by children and adolescents from all included studies examining the relationship between dietary patterns consumed and growth, body composition, and risk of obesity organized alphabetically by first-author last-name. * * ▲ Positively scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary pattern approaches included a priori index/score analysis and/or investigator-assigned intervention (RCT), a posteriori latent class (LCA) or principal component analysis (PCA), and reduced rank regression (RRR). The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 10. ^†^ † Abbreviations: AS, added sugar; C, coffee only; ch, cheese; D, included with Dairy/products; DP, dietary pattern; EDF, energy-dense food; fer, fermented; FF, fried potato or French fries; Fr, included with Fruits component; FrJ, included with Fruit Juice component; FS, included as Fish and/or Seafood; G, included with Grains/products; HF, high-fiber; L, included with Legumes component; LN, included as legumes and nuts; M, included as Meat/products; Med, Mediterranean; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; pro, protein (total/foods); RP, red and processed; SB, sugar-sweetened beverage; T, tea only; UF: SF, ratio of unsaturated relative to saturated fat; UP, ultra-processed; V, included with Vegetables; W: R, white-to-red meat ratio; X, component excluded from pattern/analyses; y, yogurt

Article; Dietary pattern approach and label | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated | Fat: Other | Fat: Saturated | Alcohol | Salty foods, Sodium Na^+^ | Tea and Coffee | Fiber | Other, A | Other, B
Agnihotri, 2021; a priori: NND 3y | ▲ | ▲ | | ▲ | ▼ | | | | | ▲ | | | | | FrJ, Milk: Juice | | | ▼
Agnihotri, 2021; a priori: NND 7y | ▲ ▲ | ▲ | | ▲ | ▼ | | ▲ | ▲ | | ▲ | | | | | FrJ, Milk: Juice | | | ▼ | | | | | | | | | ▲
Aljahdali, 2022; a priori: aMED score | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | | | | ◀
Aljahdali, 2022; a priori: DASH score | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Ambrosini, 2016; RRR: DP1 | ▼ | | | ▼ | | | ▼ | HF | ▲ | | | | | | | | | ▲ | ▲ | | | | | | | | | ▼
Ambrosini, 2016; RRR: DP2 | | | | | ▲ | | | | ▲ | | | | | | ▼ | | ▼ | ▲ | | ▼ | ▼ | | | | | | ▼
Arenaza, 2020; a priori: KIDMED score | ▲ | | ▲ | ▲ | Fr | ▲ | | ▲ | | ▲ | | | | | | | | | ▼ | ▲
Arruda, 2021; a posteriori: ‘Snacks’ | | | | | | | | ▲ | | | | ▲P | | | ▲ | | | | | | | ▲ | | | ▲
Arruda, 2021; a posteriori: ‘Traditional’ | | | ▲ | | | | | | | | | L | L
Arruda, 2021; a posteriori: ‘Western’ | | | | | | | | ▲ | | | | | | | ▲ ch | | | ▲ | ▲ | | | | | | ▼
Asghari, 2016; a priori: DASH score | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Asoudeh, 2023; RCT: Med v. Control diet | ◀ | | | ◀ | | | | ◀ | | | | ◀ | | | | | | ◀ | SB | ▲ | ▲ | | | | | ▲
Bawaked, 2020; a priori: UPF, Nova4 | | | | | SB | | | ▲ | ▲ | | | ▲ P | | | | ▲ SB | SB | ▲ | ▲ | | | | | ▲ | | | UP
Bekelman, 2021; a priori: aDASH Score | ▲ | V | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Bekelman, 2021; a priori: aMED score | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ | | | X
Bekelman, 2021; a priori: HEI-2010 | ▲ ▲ | | ▲ ▲ pro | ▲ ▲ | | | ▲ | | ▼ | L, M | L, M | ▲ pro | L, M | | ▲ | D | D | | ▼ AS | ▲ UF | ▼ | | | ▼ Na^+^
Biazzi, 2017; a posteriori: ‘DP I’ | ▲ | | ▲ | | | | | ▲ | | | | ▲ | | | | | | | | | | | | | | | | ▲
Biazzi, 2017; a posteriori: ‘DP II’ | | ▲ FF | | | | | | | | | | | | | | | | ▲ | | | | | | ▲ | | | ▲
Biazzi, 2017; a posteriori: ‘DP III’ | ▲ | | | ▲ | ▲ | | | ▲ | | | | | | | ▲ ▲ ch | | | | | | | | | | | | | ▲
Biazzi, 2017; a posteriori: ‘DP IV’ | | | | | | | | ▲ | | | | | | | ▲ | | | | | | | | | | ▲ C
Buckland, 2022; a priori: c-r-Med | ▲ | X | ▲ | ▲ | | ▲ | G | ▲ | G | ▲ | FS | ▼ | M | | ▲ | D | D | | | ▲
Bull, 2016; a posteriori: ‘Packed Lunch’ | | | | | | | | | ▲ | | | ▲ | | | | | | | ▲ | | | ▲ | | ▲ | ▲ | | ▲
Bull, 2016; a posteriori: ‘Processed’ | | | ▲ | | | | | ▲ | | ▲ | | ▲ P | | | | | | ▲ | ▲ | | | | | ▲ | | | ▲
Bull, 2016; a posteriori: ‘Traditional’ | ▲ ▲ | ▲ | | | | | | | | | | ▲ R | ▲ | | | | | | | | | | | | ▲ | | ▲ ▲
Bull, 2016; a posteriori: Healthy’, ref | ▲ | | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | ▲ y, ch | ▲ | | | | | | ▲ | | | | | ▲ ▲
Chan She Ping-Delfos, 2015 ; a priori: DGI-CA | ▲ | | ▲ | ▲ | Fr | | ▲ | ▲ | | | | ▲ NP | M, NP | | ▲ | ▲ | D | | ◀ | ▲ | ◀ | ▼ | | | | | ▲
Chang, 2021; a priori: UPF, NOVA4 | UP | | | | UP | | | | UP | | | UP | UP | | UP | | UP | UP | UP | | | UP | | UP | | | ▲ UP
Choy, 2020; a posteriori: ‘Modern’ | ▲ | ▲ | | | | | G | ▲ | G | | | ▲ NP | | | | | | | | | | | | | | | ▼
Choy, 2020; a posteriori: ‘Neotraditional’ | ▲ ▲ | | | ▲ | | | | | | | | | | | | | | | | | | | | | | | ▲ ▲
Costa, 2019; a priori: UPF, Nova4 | | | | | | | G | ▲ ▲ ▲ | G | | | ▲ P | | | | ▲ SB | SB | ▲ | ▲ | | ▲ | | | ▲ | | | UP
Costa, 2021; a priori: UPF, Nova4 | | | | | | | | | ▲ | | | ▲ P | UP | | UP | | UP | UP | UP | | | UP | | UP | | | UP
Costa, 2022; a priori: UPF, Nova4 | | | | | ▲ | | | ▲ | ▲ | | | ▲ UP | UP | | ▲ y | ▲ SB | SB | ▲ | ▲ | | | | | ▲ | | | UP
Costa, 2023; a posteriori: ‘Dairy products’ | | | | | | | | | | | | | | | ▲
Costa, 2023; a posteriori: ‘Fast food and sweets’ | | | | | | | | | | | | | | | | | | ▲ | ▲ | | | | | | ▲ | | ▲
Costa, 2023; a posteriori: ‘Healthier’ | ▲ | | ▲ | ▲ | | | | | | | ▲ | | | | | | | | | ▲ | AF | AF | | | | | ▲ ▲
Costa, 2023; a posteriori: ‘Lower intake’ | ▼ | | ▼ | ▼ | | | | | | | ▼ | | | | | | | | | ▼ | AF | AF | | | | | ▼ ▼
Cunha, 2018; a priori: UPF, Nova4 | ▲ UP | | | ▲ | | | | ▲ | ▲ | | | ▲ P | UP | | UP | | UP | UP | UP | | | UP | | UP | | | UP
Diethelm, 2014; ΔRRR1 (less healthy) | | | | ▼ | | | | | | | | ▲ | ▼ | | | | ▼ | | ▼ | | | | | ▲ | | | ▲
Diethelm, 2014; a posteriori: ΔPCA1 to ‘pancakes, convenience foods’ | | | | | | | | | | | | | | | | | | | | | | | | | | | ▲
Diethelm, 2014; a posteriori: ΔPCA2 to ‘Traditional’ | ▼ | ▲ | | | | | ▼ | ▲ | | | | ▲ | | | | | | | | | | | | | | | ▲
Diethelm, 2014; a posteriori: PCA1, ‘Healthy’ | ▲ | | | | | | ▲ | ▲ | | | | | | | | | | ▼ | | ▲ | | | | | | | | ▲
Diethelm, 2014; a posteriori: PCA2, ‘pancakes, potatoes’ | | ▲ | | | | | | ▲ | | | | | | ▲
Diethelm, 2014; RRR1 | | | ▼ | ▲ | | | ▼ | ▼ | | | | | | | ▼
Durão, 2017; a posteriori: ‘Energy-dense foods (EDF)’ | | | | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | ▲
Durão, 2017; a posteriori: ‘Healthier’ | ▲ ▲ | | | ▲ | | | | | | ▲ | | ▼ P | | | | | | ▼ | ▼ | | | | | ▼ | | | | ▲
Durão, 2017; a posteriori: ‘Snacking’ | ▼ | ▼ | | | | | | ▼ | | ▼ | | ▼ | M | ▼ | | | | | | | | | | ▲ | | | | ▼
Durão, 2022; a posteriori: ‘EDF’ | | | | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | ▲
Durão, 2022; a posteriori: ‘Healthier’ | ▲ ▲ | | | ▲ | | | | | | ▲ | | ▼ P | | | | | | ▼ | ▼ | | | | | ▼ | | | | ▲
Durão, 2022; a posteriori: ‘Snacking’ | ▼ | ▼ | | | | | | ▼ | | ▼ | | ▼ | M | ▼ | | | | | | | | | | ▲ | | | | ▼
Farhadnejad, 2018; a priori: DASH score | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Fernandez-Alvira, 2017; a posteriori: ‘Healthy’ | ▲ | ▼ FF | | ▲ | | | ▲ | | | | | | | | | | | | | | | | | | | | | ▲
Fernandez-Alvira, 2017; a posteriori: “Processed’ | ▼ | ▲ FF | | ▼ | | | ▼ | | | | | ▲ RP | | | | | | | | | | | | ▲ | | | ▲ | ▼
Fernandez-Alvira, 2017; a posteriori: ‘Sweet’ | ▼ | | | | ▲ | | ▼ | ▼ | ▲ | | | | | | ▼ NS | | | ▲ | ▲ | | | | | | | | | ▼ ▼
Gasser, 2019; a posteriori: ‘Healthy’ | ▲ | | | ▲ | | | | ▲ | | | | | | | ▲ | D | D | | | | | | | | | | ▼ | ▲
Gasser, 2019; a posteriori: ‘Unhealthy’ | | ▲ | S | | | | | | | | | ▲ R ▲ P | | | ▲ soy | | | ▲ | ▲ | | | | | ▲ | ▲ C | | ▼
Gasser, 2019; a priori: Dietary Score | ▲ | | | ▲ | | | | | | | | | | | ▲ | | | ▼ | ▼ | | ▼
González, 2023; a priori: UPF, Nova4 | | | | | | | | | ▲ | | | ▲ P | | | | | | | ▲ | | | | | | | | UP
Heerman, 2023; a priori: UPF, Nova4 | UP | | | | UP | | | | UP | | | UP | UP | | UP | | UP | UP | UP | | | UP | | UP | | | ▲ UP
Hu, 2016; a priori: APDQS | ▲ | ▼ | ▲ | ▲ | ◀ | ▲ | ▲ | | ◀ | ▲ | ◀ | ▲ RP | ▲ | ◀ | | ▲ | ▼ | ▼ | ▼ | ▲ | ◀ | ▼ | | ▼ | ▲ | | ▼ | ◀ ◀ ◀
Johnson, 2008; RRR: DP age 5y | ▼ | ▼ | | ▼ | | | ▼ | ▲ | ▲ | | | | | | ▲ | | ▲ | | ▲ | | | | | ▲ | | | | ▼
Johnson, 2008; RRR: DP age 7y | ▼ | ▼ | | ▼ | | | ▼ | ▲ | ▲ | | | | | | | | | | ▲ | | | | | ▲ | | | | ▼
Krijger, 2021; a priori: CDQS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | P | | ▲ | D | D | ▼ | | ▲ | ▲
Krijger, 2021; a priori: DASH score | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼ Na^+^
Lee 2020; RCT: mDQI score | ▲ | | ▲ pro | ▲ | | | | ▲ | | L, pro | L, pro | L, pro | L, pro | L, pro | L, pro | | | | | ◀ | ▼ | ▼ | | ▼ | | ▲ | ◀ ◀ | ▼
Lioret, 2014; a priori: DGI-CA | ▲ | | ▲ pro | ▲ | Fr | | ▲ | ▲ | | | | ▲ NP | M, NP | | ▲ | ▲ | D | | ◀ | ▲ | ◀ | ▼ | | | | | ▲
Luque, 2021; a posteriori: ‘Core Foods Pattern’ | ▲ | ▲ | | ▲ | | | | | | ▲ | | ▲ R | ▲ | | | | | | | ▲ OO | | | | | | | | ▲
Luque, 2021; a posteriori: ‘Poor-Quality Fats and Sugars’ | | ▲ | | | ▲ | | | | | ▼ | | | | | ▲ ch | | | | | ▼ | | ▲ | | | ▲ T
Luque, 2021; a posteriori: ‘Protein Sources’ | ▲ | ▲ | | | | | | | | ▲ P | | ▲ R | ▲ | ▲ | ▲ AS | AS | AS | | | | | | | ▲ | | | | ▲
Marinho, 2022; a posteriori: ‘EDF’ | | | | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | | ▲
Marinho, 2022; a posteriori: ‘Healthier’ | ▲ ▲ | | | ▲ | | | | | | ▲ | | ▼ P | | | | | | ▼ | ▼ | | | | | ▼ | | | | ▲
Marinho, 2022; a posteriori: ‘snacking’ | ▼ | ▼ | | | | | | ▼ | | ▼ | | ▼ | M | ▼ | | | | | | | | | | ▲ | | | | ▼
Marks, 2015; a priori: Non-core food score | | ▲ FF | | | | | | | ▲ ▲ | | | ▲ | | | ▲ AS | | | | ▲ ▲ | | | | | ▲ ▲ | | | ▲ ▲
Martin-Calvo, 2016; a priori: mKIDMED | ▲ ▲ | | ▲ | ▲ ▲ | Fr | ▲ | NS | ▲ ▲ | NS | ▲ | | | | | ◀ | ▲ | D | | ▼ | ▲
McCourt, 2014; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | G | ▲ | G | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ | | | ◀
Nguyen, 2020; a priori: CDQS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | P | | ▲ | D | D | ▼ | | ▲
Notario-Barandiaran, 2020; a priori: rMED | ▲ | X | ▲ | ▲ | | Fr | G | ▲ | G | ▲ | | ▼ P | ▼ | | | | | | | ▲ OO | | | X
Oellingrath, 2017; a posteriori: ‘dieting’ | | | | | | | | | | | | | | | | | | | | | | | | | | | ▲
Oellingrath, 2017; a posteriori: ‘junk convenient’ | | | | | | | | | ▲ | | | | | | | | | | ▲ | | | | | | | | ▲
Oellingrath, 2017; a posteriori: ‘snacking’ | ▼ | | | | | | ▼ | | | | | | | | | | | ▲ | ▲ | | | | | | | | | ▼
Oellingrath, 2017; a posteriori: ‘varied Norwegian’ | ▲ | | | ▲ | | | ▲ | | | ▲ | | | | | | | | | | | | | | | | | ▲ ▲
Okubo, 2015; a priori: Prudent’ (DQ score) | ▲ | V | | ▲ | | | | | | ▲ FS | FS
Pala, 2013; a posteriori: ‘Protein and Water’ | | | | | | | | | | ▲ | | ▲ | M | ▲ | | | | | | | | | | | | | ▲
Pala, 2013; a posteriori: ‘Snacking’ | | | | | | | | | | | | | | | | | | | | | | | | ▲ | | | ▲
Pala, 2013; a posteriori: ‘Sweet’ | | | | | | | | ▲ | | | | ▲ fried | | | | | | ▲ | ▲ | | | | | | | | ▲
Pala, 2013; a posteriori: ‘Vegetables and Wholemeal | ▲ | | | ▲ | | | ▲ | | | | | | | | | ▲ NS | NS | | | | | | | | | | | ▲
Papamichael, 2019; RCT: Med v. Control diet | ◀ ◀ | | | ◀ | | ◀ | | ▲ | | ▲ | ◀ | ◀ | M | | ◀ | D | D | ◀ | ◀ | ◀ | | | | ◀
Pinto, 2021; a posteriori: ‘fish based’ | | | | | | | | | | ▲ | | | | | | | | | | | | | | | | | ▼
Pinto, 2021; a posteriori: ‘DASH diet based’ | ▲ | | | ▲ | | | | | | ▲ | | | | | ▲ | D | D | | | | | | | | | | | ▲
Pinto, 2021; a posteriori: ‘energy-dense foods’ | ▼ | | | | | | | ▲ | | | | ▲ RP | | | | | | | | | | | | | | | | ▼
Pinto, 2021; a posteriori: ‘regression analysis (no label) | | | | | | | | ▲ | | | | | | | ▲ ch, y | | | ▲
Pinto, 2021; a posteriori: ‘Western’ | ▼ | | | ▼ | | | | | | ▼ | | | | | | | | ▲ | ▲ | | | | | ▲ | | | | ▼
Rashid, 2020; a posteriori: ‘Full-fat’ | | | | | | | | ▲ | | | | | | | | | | | | | ▼ | ▲
Rashid, 2020; a posteriori: ‘Healthy’ | ▲ | | | ▲ | | | | | | ▲ | | | | | | | | | | | | | | | ▲ T | | ▲ ▲
Rashid, 2020; a posteriori: ‘Meat’ | | | | | | | | | ▲ | | | ▲ | M | | | | | | | | | | | | | | ▲
Rashid, 2020; a posteriori: ‘Snacking’ | | | | | | | ▼ | | ▲ | | | | | | | | | | ▲
Saldanha-Gomes, 2017; a posteriori: ‘Guidelines’ | ▲ | ▲ | | ▲ | | | | ▲ | ▲ | ▲ | | ▲ | M | | | | | | | | | | | | | | ▲ | ▲
Saldanha-Gomes, 2017; a posteriori: ‘Processed, fast foods’ | ▼ | ▲ FF | ▲ | | ▲ | | | ▲ | | | | ▲ P | | | ▲ | | | ▲ | | | | | | ▲ | | | ▲ | ▼
Saldanha-Gomes, 2022; a posteriori: ‘Nutrient-dense foods’ | ▲ | | | ▲ | | | | ▲ | ▲ | | | ▲ RP | | | | | | | | | | | | | | | | ▲
Saldanha-Gomes, 2022; a posteriori: ‘Processed and fast foods’ | ▼ | ▲ FF | ▲ | | ▲ | | | ▲ | | | | ▲ P | | | ▲ | | | ▲ | | | | | | ▲ | | | ▲ | ▼
Santos, 2019; a posteriori: ‘Beverages’2y | | | | | ▲ | | | | | | | | | | | | | | | | | | | | ▲ T | | ▲
Santos, 2019; a posteriori: ‘Beverages’4y | | | | | ▲
Santos, 2019; a posteriori: ‘Meat and vegetables’2y | ▲ | ▲ | ▲ | ▲ | | | | | | | | ▲ | M | | | | | | | | | | | | | | | ▲
Santos, 2019; a posteriori: ‘Milks’ 2y | | | | | | | | | | | | | | | | ▼ | | | | | | | | | | | ▲
Santos, 2019; a posteriori: ‘Milks’ 4y | | | | | | | | | | | | | | | | ▲ | | | | | | | | | | | ▲
Santos, 2019; a posteriori: ‘Snacks’2y | | | | ▼ | | | | ▲ | | | | | | | ▼ y | | | | | | | | | | ▲
Santos, 2019; a posteriori: ‘Snacks’4y | | | | | | | | ▲ | | | | | | | ▼ y | | | ▼ | | | | | | | ▲ | | ▲
Santos, 2019; a posteriori: ‘Staple’2y | | | ▲ | | | | ▲ | ▼
Santos, 2019; a posteriori: ‘Staple’4y | | | ▲ | | | | ▲ | | | | | ▲ R
Santos, 2019; a posteriori: ‘Treats’4y | | | | | | | | | | | | | | | | | | | ▲ | | | | | | | | ▲
Setayeshgar, 2017; a priori: mDQI | ▲ | | | ▲ | | | | ▲ | | | | | | | | | | | | ◀ UF: SF | ▼ | ▼ | | ▼ Na^+^ | | ▲ | ◀ ◀ | ▼
Shinsugi, 2020; a priori: modified Japanese Food Guide score | ▲ | | | ▲ | | | | ▲ | | ▲ | | W:R | ▲ W:R | | ▲ | | | | | | | | ▼ | Na^+^ | | | ▼
Siddiqui, 2022; a priori: CDQS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | P | | ▲ | D | D | ▼ | | ▲
Sirkka, 2021; a posteriori: ‘Minimally processed foods’ | ▲ | | | | | | | ▲ | | | | | | | | | | | | | | | | ▲ | | | ▲
Sirkka, 2021; a posteriori: ‘Ultra- processed foods’ | | | | | | | ▼ | ▲ | | | | | | | | | | ▲ | | | | | | ▲
Smith, 2014; a posteriori: ‘Packed Lunch’ | | | | | | | | | ▲ | | | ▲ | M | | ▲ ch | | | | | | ▲ | | | ▲ flavor | | | ▲
Smith, 2014; a posteriori: ‘Traditional’ | ▲ ▲ | | | | | | | ▲ | | | | ▲ | M | | | | | | | | | | | | | | ▲
Smith, 2014; a posteriori: ‘Health Aware’ | ▲ | ▼ FF | | V | | | ▲ HF | HF | | ▲ | | ▼ P | | | ▲ ch | | | ▼ | | | | | | ▼ | | | | ▲ V
Sorensen, 2021; a priori: children’s DQI | ▲ | G | | ▲ | ▼ | | G | ▲ | G | ▲ M | | M | M | | ▲ ch | ▲ D | D | ▼ | ▼ | | | | | ▼ | SB | | ▼
Sorensen, 2021; a priori: mMDS | ▲ VL | | VL | ▲ | | Fr | G | ▲ | G | ▲ | | ▼ | M | | ▼ | D | D
Temple, 2023; a priori: DGA-2020-2025 | ▲ | | ▲ pro | ▲ | | | ▲ | | | L | L | L | L | | ▲ | D | D | | ▼ AS | | | ▼ | | ▼ Na^+^ | | | ▲
Tognon, 2014; a priori: fMDS | ▲ VL | | VL | ▲ | | Fr | G | ▲ | G | ▲ | | ▼ | M | | ▼ | D | D
Vallejo, 2022; a priori: DI score (EAT-Lancet) | ▲ | ◀ | ▲ | ▲ | | ▲ | ▲ | | | ◀ | | ▼ RP | ▼ | ▼ | ▼ | D | D | | ◀ | ◀ | ◀ | ◀
Vedovato, 2021; a priori: UPF, Nova4 | UP | | | | UP | | | | UP | | | UP | UP | | UP | | UP | UP | UP | | | UP | | UP | | | ▲ UP
Vilela, 2022; a priori: UPF, Nova4 | | | | SB | | | | ▲ | ▲ | | | ▲ P | UP | | UP | | UP | UP | UP | | | UP | | UP | | | UP
Vinke, 2020; a priori: LLDS | ▲ | | ▲ | ▲ | | LN | ▲ | | | ▲ | | ▼ RP | | | ▲ NS | D, NS | D, NS | ▼ | | ▲ | ▲ | ▼ | | | ▲
Wolters, 2018 IDEFICS; ΔRRR1 | | | | ▼ | | ▼ | | ▼ | ▲ | | | ▼ | M | ▼ | | | | ▼
Wolters, 2018 IDEFICS; a posteriori: ΔPCA1 to PCA2 | | | | ▲ | | ▲ | G | ▲ | G | | | ▲ fried | fried | | ▲ y ▲ fer | | | | | | | | | | | | ▲
Wolters, 2018 IDEFICS; a posteriori: ΔPCA2 to ‘Traditional’ | ▲ | ▲ | ▲ | ▲ | | | | | | | | | | | | | | ▲ | | | ▲ | ▲ | | | | | | ▲
Wolters, 2018 IDEFICS; a posteriori: ΔPCA3 twds PCA1 | | | | | | | | | | | | | | | ▲ | | | ▲ | ▲ | | | | | ▲
Wolters, 2018 IDEFICS; a posteriori: PCA2 ‘Med type’ | | | | ▲ | | ▲ | G | ▲ | G | | | ▲ not fried | not fried | | ▲ ch, y, NS | ▲ NS | NS | | | | | | | | | | ▲
Wolters, 2018 - IDEFICS; RRR1, ‘nuts, meat, pizza’ | ▲ | ▼ | ▼ | ▲ | | ▲ | | ▼ | ▼ | | | ▲ | M | | ▲ | | | | ▲ | | | | | ▲ | | | ▲ ▲ | ▼ ▼
Wolters, 2018 - KOPS; a posteriori: ΔPCA1 | | ▲ | | | | | | ▲ | | ▲ P | | ▲ | | | | | | | | | | | | | | | ▲
Wolters, 2018 KOPS; a posteriori: ΔPCA2 | ▲ | ▲ | | ▲ | | | | | | | | ▲ | M | | | | | | | | | | | | | | | ▲
Wolters, 2018 - KOPS; a posteriori: PCA 1 ‘Fast food’: | | ▲ | | | | | | ▲ | | ▲ | | ▲ | | | | | | | | | | | | | | | ▲
Wolters, 2018 KOPS; a posteriori: PCA 2 ‘Healthy’ | ▲ | | | ▲ | | | ▲ | ▲ | | | | | | | ▲ ch, y | | | | | | | | | | | | | ▲
Wolters, 2018 KOPS; RRR1, ‘Fast food’ | ▲ | ▲ | | | | | ▼ | | | ▲ | | ▲ | ▲ | | ▼ | | | ▲ | | | | | | | | | ▲
Wolters, 2018 IDEFICS; a posteriori: PCA 1 ‘Snack’ | | ▲ | | | | | | | | | | | | | ▲ | | | ▲ | ▲ | | | | | ▲ | | | ▲
Wolters, 2018 KOPS; ΔRRR1 ‘Increased fast food, starchy CHO | ▼ | ▲ | | | | | ▲ | | | ▲ | | | | | | | | | | | | | | | | | ▲ | ▼
Wolters, 2018 KOPS; a posteriori: ΔPCA3 | | | | | | | ▼ | ▲ | | | | | | | | | | | | | | | | ▲

## Adults and older adults

Table A 10 Visualization of dietary pattern components across dietary patterns from intervention studies evidence in adults and older adults examining the relationship between dietary patterns consumed and body composition and risk of obesity organized by first-author last-name alphabetically^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as par of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern. Dietary approaches included in this table are a priori investigator-assigned diet intervention and/or index/score analysis. The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 14. ^†^ † Abbreviations: AF, added fat; AP, animal products; AS, added sugar; C, coffee; ch, cheese; D, dairy/products; DG, dietary guidelines; DP, dietary pattern; evo, extra-virgin olive oil; fer, fermented; FF, fried potato or French fries; Fr, included with Fruit component; FS, fish and seafood; G, grains or grain products; HF, high-fiber; LN, legumes and nuts; M, meat/ products; Na+, sodium; NP, not processed; NS, not sweetened; oo, olive oil; P, processed; pro, protein (total/foods); RP, red and processed; rw, red wine; SB, sugar-sweetened beverage; SF, saturated fat; SO, sunflower oil; T, tea; Tr, Trans fat; UF, unsaturated; UP, ultra-processed; V, vegetable; VO, vegetable oil; w, wine; W:R, white-to-red meat ratio; X, component excluded from the dietary pattern; y, yogurt

Article; Dietary pattern comparison | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Sodium | Tea and Coffee | Other, A | Other, B
Alvarez-Perez, 2016; RCT: Med+Evo arm | ▲ | | ▲ | ▲ | ▲ | ◀ | ◀ | ▲ | | ▲ | FS | ▼ RP | ▲ W: R | ◀ | ▼ | ◀ ch | | | | ▲ evo | | | ◀ w | | | ▲ V | ◀
Alvarez-Perez, 2016; RCT: Med+Nuts arm | ▲ | | ▲ | ▲ | ▲ | ▲ | ◀ | ▲ | | ▲ | FS | ▼ RP | ▲ W: R | ◀ | ▼ | ◀ ch | | | | ▲ oo | | | ◀ w | | | ▲ V | ◀
Arjmand, 2022; RCT: MIND v. Control diets (calorie-restricted) | ▲ | | ▲ | ▲ | | ◀ | ▲ | | | ▲ not fried | | ▼ R | F | | ▼ | | | | ▼ | ▲ oo | | ▼ | ▲ w | | | ▼
Bruno, 2020; MEDAS in IG v. Control | ▲ | | ▲ | ▲ | | ▲ | | | ▼ | ▲ | | ▼ RP | ▲ W: R | | | | | ▼ | | ▲ oo ▲ oo to cook | | ▼ | ▲ rw | | | ▲ V
Calvo-Malvar, 2021 A; RCT: ‘Alcohol’ | | | | | | | | | | | | ▲ P | | | | | | | | ▲ oo | | | ▲ ▲ ▲ | | ▲ C
Calvo-Malvar, 2021 A; RCT: ‘Caloric’ | | | | | | | | | | | | ▲ P | | | | | | ▲ | ▲ | | | | ▼ w | ▲ salty food | | ▲
Calvo-Malvar, 2021 A; RCT: ‘Fish and Boiled Meals’ | ▲ ▲ | ▲ boil | ▲ | | | | | | | ▲ not fried ▲ fried | FS | ▲ not fried | | ▲ not fried ▲ fried | | | | | | ▲ SO
Calvo-Malvar, 2021 A; RCT: Fried’ | | ▲ fried | | | | | ▼ | | ▲ | ▲ fried | | ▲ fried | | | | ▼ | ▲ | | ▲ | ▲ SO
Calvo-Malvar, 2021 A; RCT: ‘Fruits, Vegetables, and Dairy Products’ | ▲ | | | ▲ | | ▲ | ▲ | | | | | | | | | ▲ | | | ▲ | ▲ oo | | | | | ▲ T | ▲
Calvo-Malvar, 2021_B; IG v. Control | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | ▲ | ▼ | ▲ | FS | ▼ RP | ▲ | ▲ | ▲ | | | | ▼ | ▲ oo | ▼ | ▼ | ◀ w | | | ▲
Casas, 2022; RCT: MedDiets v. Control | ▲ Q1 | | ▲ | ▲ | ▲ | | | | | ▲ | FS | | | | | | | | | | | | | | ▲ T
Crosby, 2022; AHEI-2010 | ▲ | | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Crosby, 2022; RCT: Low-Fat Vegan v. Control | ▲ | | ▲ | ▲ | | | ▲ | | | ▼ AP | AP | AP | AP | AP | AP | AP | AP | | | | ▼ AF
Davis, 2017; RCT: Med diet | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ◀ | | ▼ RP | | | ◀ ch, y | | | | | ▲ evo | ◀ | | ◀ w
Estruch, 2019; RCT: MEDAS, Med+EVOO v. Control | ▲ | | ▲ ▲ | ▲ | ▲ | ◀ | ▲ | | | ▲ | FS | ▼ RP | ▲ W: R | ◀ | ▼ | ◀ ch | | | | ▲ oo | | | ◀ w | | | ▲ V | ◀
Estruch, 2019; RCT: MEDAS, Med+Nuts v. Control | ▲ | | ▲ ▲ | ▲ | ▲ | ▲ | ▲ | | | ▲ | FS | ▼ RP | ▲ W: R | ◀ | ▼ | ◀ ch | | | | ▲ oo | | | ◀ w | | | ▲ V | ◀
Georgoulis, 2020; 2021; 2023; MDG v. SCG had higher MedDietScores | ▲ | | ▲ | ▲ | | | ▲ | | | ▲ | FS | ▼ R ▼ P | ▲ | | ▲ | | | ▼ | ▼ | ▲ oo | | | ◀ | ▼ salt
Gotfredsen, 2021; RCT: OFF v. HAB | | | | | | | | | | | | | | | | | | | | | | ▼
Gotfredsen, 2021; RCT: SUB v. HAB | ▲ | | | | | | ▲ | | | | | | | | | | | | | ▲ | | ▼ | | | | ▲ | ▼ V
Jenkins, 2017; RCT: Advice group | ▲ | | ▲ soy | ▲ | | ▲ | ▲ | | | | | ▼ | ▼ | | | | | ▼ | ▼
Lima, 2013; DASH diet v. Control | ▲ | ▲ | ▲ | ▲ | | | | ▲ | | ▲ | | ▼ | ▼ | | | ▲ | | ▼ | | | | | | ▼ salt
Luo, 2022; RCT: ‘Med Diet’ (MD) | ▲ | | ▼ soy | ▲ | | ▲ | ▲ | | ▼ | ▲ | | ▼ | ▲ | | | | | | | ▲ evo | ▼ SO
Luo, 2022; RCT: Control Diet (CD) | ▼ | | ▼ soy | ▼ | | ▼ | ▼ | ▲ | ▲ | ▼ | | ▲ | ▲ | | | | | | | ▼ oo | ▲ SO
Luo, 2022; RCT: ‘Traditional Jiangnan Diet (TJD, traditional of SE China | ▲ | | ▲ | ▲ | | ▼ | ◀ | | ▲ | ▲ | ▲ | ▼ | ▼ | | | | | | | | ▲ SO
Maruyama, 2021; RCT: ‘Japan Diet (JD) | ▲ | | ▲ | | | | ▲ | | | ▲ | | ▼ | ▼ | | | | | | ▼ | | | ▼ | ▼
Maruyama, 2021; RCT: ‘Partial JD’ (PJD) | | | | | | | | | | | | ▼ | ▼ | | | | | | ▼ | | | ▼ | ▼
Murphy, 2022; RCT: MedDiet | ▲ | ▼ | ▲ | ▲ | | ▲ | ▲ | | | ◀ | | ▼ R | | ▼ | ▼ | D | D | ▼ | SB | ▲ oo | ◀ | ▼ | ◀ rw | | | ▼ ▼
Pattinson, 2020; RCT: FBG vs. TMR | | | | ▲ | | | | | | | | | | | | | | | | | | | | | ▲ | ▼
Pattinson, 2020; HEIFA score | ▲ ▲ | | M, D | ▲ ▲ | | ▲ | ▲ | ▲ | | | | ▼ P | | | ◀ | | | ▼ | ▼ | ▲
Pattinson, 2020; RCT: TMR v. FBG | | | | ▼ | | | | | | | | | | | | | | | | | | | | | ▲ | ▲
Pavic, 2019; RCT: Med diet (MD) v. SHD | | | | | | ▲ | | | | ▲ | | | | | | | | | | ▲ oo
Poulsen, 2015; RCT: New Nordic diet intervention | ▲ | ▲ | | ▲ | | ▲ | ▲ | | | ▲ | ▲ | ▲ | M | | | | | | | | | | | | | ▲ V
Reidlinger, 2015; RCT: DG v. CG | ▲ | | | ▲ | | | ▲ | | | ▲ | | ▼ | | | | | | ▼ | ▼ | | ▼ | ▼ | ◀ | ▼ salt
Sidahmed, 2014; RCT: ‘Healthy eating’ | ▲ | | | ▲ | | | ▲ | | | | | | | | | | | | | ▼
Sidahmed, 2014; RCT: ‘Med.’ | ▲ | | | ▲ | | | ▲ | | | | | | | | | | | | | ▲
Turner-McGrievy, 2015; RCT: ‘Pesco-vegetarian’ | ▲ | | ▲ | ▲ | | | ▲ | | | ◀ | ◀ | ▼ | ▼ | ◀ | ◀ | ◀ | ◀
Turner-McGrievy, 2015; RCT: ‘Semi-vegetarian’ | ▲ | | ▲ | ▲ | | | ▲ | | | ◀ | ◀ | ◀ | ◀ | ◀ | ◀ | ◀ | ◀
Turner-McGrievy, 2015; RCT: ‘Vegan’ | ▲ | | ▲ | ▲ | | | ▲ | | | ▼ AP | AP | AP | AP | AP | AP | AP | AP
Turner-McGrievy, 2015; RCT: ‘Vegetarian’ | ▲ | | ▲ | ▲ | | | ▲ | | | ▼ | ▼ | ▼ | ▼ | ◀ | ◀ | ◀ | ◀
Tussing-Humphreys, 2022; MedDiet Score | ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ | ▼ | | | | ▼ | | | ▲ oo | | | ◀ w
Van Horn, 2020; RCT: IG v. Usual diet | ▲ | | ▲ | ▲ | | | | ▲ | | | | | | | | ▲ | | | | | ▼

Table A 11 Visualization of dietary pattern components from observational studies that examined dietary patterns consumed by adults and older adults and body composition and risk of obesity organized alphabetically by first-author last name^*^ * ▲ Positively-scored component, reflecting higher intake within the food category as part of the pattern; ▼ Negatively-scored component, reflecting lower intake within the food category as part of the pattern; ◄ Neutral component, reflecting moderate (in contrast to higher or lower) intake within the food category as part of the pattern ,^†^ † Dietary approaches included methods such as a priori index/score analysis, a posteriori such as principal component analysis (PCA), and reduced rank regression (RRR). The dietary pattern labels are abbreviated in this table due to limited space, but full details about each dietary pattern are described in Table 16

Article; Dietary pattern approach and label | Vegetables | Potato | Legumes | Fruit | Fruit Juice | Nuts, Seeds | Grains: Whole | Grains | Grains: Refined | Fish | Seafood, shellfish | Meats (Red Processed) | Lean meats (Poultry) | Eggs | Dairy | Dairy: Low, non-fat | Dairy: Whole, high fat | Sugary Beverages | Sugary foods | Fat: Unsaturated, Oils | Fat: Other | Fat: Saturated | Alcohol | Sodium | Tea and Coffee | Other, A | Other, B
Agnoli, 2018; a priori: IMI | ▲ | | ▲ | ▲ | | | | ▲ | | ▲ | | ▼ R | | | | | | ▼ | | ▲ oo | | ▼ | ◀
Alae-Carew, 2020; a posteriori: ‘Stage 1’ | X | ▲ | X | ▼ | | | | | ▼ | | | | ▼ | ▼ | ▼ | | | | | | | | | | | ▼ UP | ▲
Alae-Carew, 2020; a posteriori: ‘Stage 2’ | ▼ | ▲ | ▼ | ▼ | | | ▼ | | ▼ | | | ▼ R | ▼ | ▼ | ▼ | | | | | | | | | | | ▼ UP | ◀
Alae-Carew, 2020; a posteriori: ‘‘Stage 3’, ref | ▼ | ◀ | ◀ | ◀ | | | | | ◀ | | ▲ | ◀ R | ◀ | ▼ | | | | | | | | | | | | ▲ UP | ◀ UP
Alae-Carew, 2020; a posteriori: ‘Stage 4’ | ▲ | | ◀ | | | | | | ◀ | | | ▲ R ◀ R | ▲ | | ▲ | | | | | | | | | | | ▲ UP | ◀
Aljadani, 2020_F; a priori: ARFS | ▲ | | ▲ pro | ▲ | | pro | | ▲ | | pro | | ▼ | ▼ | pro | | ▲ | | | | | ◀ | | ◀
Aljadani, 2020_I; a priori: ARFS | ▲ | | ▲ pro | ▲ | | pro | | ▲ | | pro | | ▼ | ▼ | pro | | ▲ | | | | | ◀ | | ◀
Allaire, 2020; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Andre, 2020; a priori: LitMDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ | | | ▼ | | | | | ▲ oo | | | ◀
Angulo, 2021; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Angulo, 2021; a priori: GDQS | ▲ ▲ ▲ | ▼ | ▲ | ▲ ▲ ▲ | ▼ SB | ▲ | ▲ | | ▼ | ▲ FS | FS | ▼ R ▼ P | ▲ | ▲ | | ▲ | ▼ | ▼ | ▼ | ▲ | | | | | | ▼
Arabshahi, 2017; a posteriori: ‘Fruit/vegetable’ | ▲ | | ▲ | ▲ | | | ▲ | ▲ | ▼, ♀ | ▲ | FS | ▲ | ▲ | | | ▲ | | | | | | ▼ | | | | ▼ | ▲
Arabshahi, 2017; a post.:‘Meat/fat’ | | ▲ hot | ▼ | ▼ | | | ▼ | ▼, ♂ | ▲ | | | ▲ RP | ▼ | ▲ fried | | ▼ | ▲ | | | | ▲ | ▲ | | ▲ salty food | ▼ T, ♀ | ▲ ▲
Baldwin, 2020; a priori: ARFS | ▲ | | ▲ pro | ▲ | | pro | | ▲ | | pro | | ▼ | ▼ | pro | | ▲ | | | | | ◀ | | ◀
Baratali, 2021; a posteriori: ‘Fatty & Sugary’ | | | | | | | | ▲ | | | | | | | | | | | | | | ▲ | | | | ▲
Baratali, 2021; a posteriori: ‘Fruits & Vegetables’ | ▲ | | | ▲ | Fr
Baratali, 2021; a posteriori: ‘Meat & Fries’ | | ▲ FF | | | | | | | | | | ▲ RP | ▲
Baratali, 2021; a priori: aHEI | ▲ | X | ▲ soy | ▲ | | LN | | | | | | W: R | ▲ W: R | | | | | | | ▲ UF: SF | ▼ Tr | UF: SF | ◀ | | | ▲ ▲
Baratali, 2021; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF: SF | | UF: SF | ◀
Baratali, 2021; a priori: mMDS | ▲ ▲ | | | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀
Beslay, 2020; a priori: UPF, Nova4 | ▲ UP | | V | V | SB | | | ▲ UP | G | | M, P | ▲ RP | M, P | M, P | ▲ UP | | | ▲ | ▲ | | ▲ | AF | | ▲ salty food
Best, 2023; a priori: EWG | ▲ VF | | | VF | | | | | | ▲ ▲ | | ▼ RP | | | | | | ▼ | | | | ▼ | | ▼ salt | | ▲
Best, 2023; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF: SF | | UF: SF | ◀
Bouzas, 2020; a priori: MedDiet, m | ▲ | | ▲ | ▲ | ▼ SB | ▲ | ▲ | | ▼ ▼ | ▲ FS | FS | ▼ RP | ▲ | | | | ▼ | ▼ | ▼ | ▲ evo | | ▼ | ▲ w | | | ▲ ▲
Bouzas, 2020; a priori: Proveg. | ▲ | | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▼ | | ▲ oo | | ▼ | | | ▲ C | ▼ AP
Bouzas, 2022; a priori: MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ RP | ▲ W: R | | | | | ▼ | ▼ | ▲ oo ▲ oo to cook | | ▼ | ▲ w | | | ▲
Brayner, 2021; RRR: ‘DP1’ | ▲ | | | ▼ | | ▲ | | | | | | | | | | ▼ | | | | | | ▲
Brayner, 2021; RRR: ‘DP2’ | | | | | | ▼ | | | | | | | | | | | ▲ | | | | | ▲
Canhada, 2019; a priori: UPF, Nova4 | | | | | SB | | | ▲ | ▲ ▲ | | | ▲ P | M, P | | ▲ y | | | ▲ | ▲ | | ▲ | ▲ | ▲ | ▲ salty food | | ▲ ▲
Cespedes Feliciano, 2016; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Cespedes Feliciano, 2016; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀
Cespedes Feliciano, 2016; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Cespedes Feliciano, 2016; a priori: HEI-2010 | ▲ ▲ L | V | V, pro | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | ▼ | SB | ▲ UF | | ▼ | | ▼
Chaltiel, 2019; a priori: PNNS-GS2, m | ▲ | ◀ | ▲ | V | | ▲ | ▲ | ◀ | | ▼ FS | ◀ | ▼ R ▼ P | ◀ | ◀ | ▲ | D | D | ▼ | ▼ | | ▼ A F | | ▼ | ▼ salt
Chen, 2019; a priori: PDI, m | ▲ ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | ▼ FS | | ▼ RP | ▼ | ▼ | ▼ | ▼ | ▼ | ▲ | ▲ | ▲ VO | | ▼ | ▲ | | ▲ | ▼ AP
Choi, 2020; a priori: APDQS | ▲ | ◀ | ▲ | ▲ | ◀ | ▲ | ▲ | | ◀ | ▲ ▼ Fried | ◀ | ▼ | ▲ | ◀ | | ▲ | ▼ | ▼ | ▼ | ▲ | ◀ | ▼ | ▲ | ▼ salty food | ▲ | ◀ ◀ ◀ ◀ ◀ ◀ ◀ | ▼ FF ▼
Cordova, 2021; a priori: Q5 v. Q1 UPF, Nova4 | ▲ UP | ▲ | ▼ | ▼ | SB | | | ▲ UP | ▲ | ▼ | | ▲ RP | M, P | ◀ | ▲ UP | | ▲ | ▲ | ▲ | | ◀ AF | ▲ | X | ▲ salty food | ◀ C | ▲ UP
Cuenca-Garcia, 2014; a priori: DQI | ▲ | | G | V | | | | ▲ | | | | | | | | | | | | | ▼ | ◀ ◀ | | ▼ | | ▲ pro
Cuenca-Garcia, 2014; a priori: IDIs | ▲ | | ▲ | V | | LN | ▲ | | | ▲ | | ▼ p | | | | | | ▼ | SB | | | ▼ | | ▼
Cuenca-Garcia, 2014; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | | | | | ▲ UF: SF | | UF: SF | ◀
Ericson, 2019; a posteriori: ‘Dressing-Vegetables’ | ▲ | ▲ fried | | | | | | ▲ | | | | | ▲ | | ▲ ch | | | ▼ | | | ▲ | | | ▲ salty food | | ▼
Ericson, 2019; a posteriori: ‘Health-Conscious’ | ▲ | | | ▲ | | | ▲ HF | ▲ | ▼ | ▲ | | ▼ RP | | | ▲ | ▲ y | | ▼
Ericson, 2019; a posteriori: ‘Low-Fat Products’ | | | | | | | | | | | | | | | | ▲ y ▲ milk | | | | | ▲ | ▼
Ford, 2017; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀ 4/wk
Ford, 2017; a priori: HEI-2010 | ▲ ▲ L | V | V, pro | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | AS | ▼ | ▲ | | ▼ | ◀ | ▼
Ford, 2017; a priori: Low-fat | ▲ | | | ▲ | | | | ▲ | | | | | | | | | | | | | | | ◀ 3/wk
Ford, 2017; a priori: Reduced-carbohydrate | ◀ | | | ◀ | | | | ◀ | | | | | | | | | | | | | | | ▲ 6/wk
Fung, 2015; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Fung, 2015; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Fung, 2015; a priori: modified aMED | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Fung, 2021; a priori: GDQS | ▲ ▲ ▲ | ▼ | ▲ | ▲ ▲ ▲ | ▼ SB | ▲ | ▲ | | ▼ | ▲ FS | FS | ▼ R ▼ P | ▲ | ▲ | | ▲ | ▼ | ▼ | ▼ | ▲ | | | | | | ▼
Funtikova, 2014; a priori: MDS-rec, Spain | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | M | | ▼ | | | | | ▲ oo | | | ◀ rw
Funtikova, 2014; a priori: mMDS or R-MDS, Spain | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | M | | ▼ | | | | | ▲ oo | | | ◀ rw
Glenn, 2021; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Gómez-Donoso, 2018 A; a priori: DOS | ▲ | | ▲ | ▲ | | ▲ | | | ▼ | ▲ FS | FS | ▼ RP | | | ▲ y | | | ▼ | | | | ▼ | ▼ | | | ▼ UP
Gómez-Donoso, 2019 a; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Gómez-Donoso, 2019 a; a priori: uPDI, variants | ▼ | ▲ | ▼ | ▼ | ▼ | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ VO | | ▼ | | | ▼ | ▼ AP
Gómez-Donoso, 2019 a_Proveg; a priori: Proveg. FP | ▲ | ▲ | ▲ | ▲ | | ▲ | | ▲ | | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | | | ▲ oo | | ▼
Gómez-Donoso, 2019 b; a priori: SENC-FP | ▲ | | ▲ pro | ▲ | | pro | ▲ | WG | | pro | pro | ◀ RP | pro | pro | ▲ | D | D | | ◀ | ▲ oo | ◀ AF | | ◀ fer | ◀ salty food | | ▲
Hennein, 2019; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Hennein, 2019; a priori: aMED, m | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀
Hodge, 2021; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Hodge, 2021; a priori: MDS, m | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ oo | | | ◀
Huo, 2023; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Huo, 2023; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | ▼ | | ▼ | | | ▼ | ▼ AP
Jennings, 2020; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀
Jennings, 2020; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF: SF | | UF: SF | ◀
Johns, 2015; RRR: “Energy Dense, High Sat. Fat, Low Fiber” | ▼ | ▲ | | ▼ | | ▲ | ▼ | ▼ | ▲ | ▼ | | ▲ | ▲ | ▲ | ▲ milk | ▼ y | ▲ y, ch | ▲ | ▲ | ▲ | ▲ | | ▲ | | | ▲ | ▼
Jung, 2022; a priori: hPDI, m | ▲ ▲ | ▼ | ▲ | ▲ | | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▼ | ▼ | | | ▼ | | V | ▲ | ▼ AP
Jung, 2022; a priori: PDI | ▲ ▲ | ▲ | ▲ | ▲ | | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | | | ▼ | | V | ▲ | ▼ AP
Jung, 2022; a priori: uPDI, m | ▼ ▼ | ▲ | ▼ | ▼ | | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | | | ▲ | ▲ | | | ▼ | | V | ▼ | ▼ AP
Kanerva, 2018; a priori: BSD | ▲ | X | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | | | | | | | | | ▲ | | ◀
Kang, 2021; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Kang, 2021; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀
Kang, 2021; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Kang, 2021; a priori: HEI-2015 | ▲ ▲ VL | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | ▼ | SB | ▲ UF: SF | | ▼ | | ▼
Khoury, 2022; a priori: FSAm-NPS | ▼ | | V | V | | V | | | | | | | | | | | | AS | ▲ | ▼ oo ▼ ▼ | | ▲ | | ▲ | | ▲ | ▼
Kim, 2020; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | Fr | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | | | ▼ | | ▼ | ▲ | ▼ AP
Kim, 2020; a priori: PDI | ▲ | ▲ | ▲ | ▲ | Fr | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | ▲ salty food | ▲ | ▼ AP
Kim, 2020; a priori: Proveg. FP | ▲ | ▲ | ▲ | ▲ | | ▲ | | ▲ | | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | | | X | | ▼
Kim, 2020; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | Fr | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | | | ▼ | | ▼ salty food | ▼ | ▼ AP
Konieczna, 2019; a priori: MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | ▼ | ▲ | | ▼ RP | ▲ W: R | | | | | ▼ | | ▲ oo ▲ oo to cook | | ▼ | ▲ rw | | | ▲ V
Konieczna, 2021; a priori: UPF, Nova4 | | | | | | | | | | | | ▲ P | | | ▲ | | | ▲ | SB | | | | ▲ | | ▲ | ▲ ▲ ▲
Li, 2015 BJN; a priori: HNFI | ▲ | ▲ | | ▲ | | | ▲ ▲ | | | ▲
Li, 2015 BJN; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF: SF | | UF: SF | ◀
Li, 2016 DP; a posteriori: ‘ADA, ‘Animal offal/dessert/alcohol’ | | | | | | | | | | ▲ | ▲ | ▲ R ▲ | ▲ | | | | | | ▲ | | | | ▲ | | | ▲
Li, 2016 DP; a posteriori: ‘Meat’ | | | | | | | | ▲ | | | | ▲ R | ▲ | ▲
Li, 2016 DP; a posteriori: ‘Vegetable’ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | | | ▲ | | | | | | | | | | ▲ T | | ▲
Li, 2021; a priori: UPF, Nova4 | | | ▲ soy | | | | | ▲ | ▲ ▲ | | | ▲ | | | | | | | ▲ | | | | ▲ L | AS
Li, 2022; RRR: ‘Healthy’ (HDP) | ▲ ▲ | ▲ | ▲ soy | ▲ | | ▲ | ▲ | ▼ | ▲ | ▲ | ▲ | ▼ | ▲ | ▲ | ▲ | ▲ milk | ▲ milk | ▲ | SB | ▲ | ▲ | ▲ | | V, FS | | ▲ ▲ M, P
Li, 2022; RRR: ‘Unhealthy’ (UHDP) | ◀ ◀ | ▲ | ▲ soy | ▲ | | ◀ | ▲ | ▲ | | ◀ | ◀ | ◀ | ◀ | ◀ | ◀ | ◀ milk | ▲ milk | ▲ | SB | ◀ | ◀ | ◀ | | V, FS
Lim, 2021; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | | | ◀
Lim, 2021; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼
Liu, 2022; a posteriori: ‘Grain-vegetable’ | ▲ | | | | | | G | ▲ | G
Liu, 2022; a posteriori: ‘High-salt and high-oil’ | | | ▲ | | | | | | | | | | | | | | | | | | ▲ | | | | | ▲ V
Liu, 2022; a posteriori: ‘Junk food’ | | | | | | | | | | | | | | | | | | ▲ | ▲ | | | | | | | ▲
Liu, 2022; a posteriori: ‘Western’ | | ▲ | ▲ | | | | | | | ▲ | | ▲ | M | ▲ | ▲ milk
Liu, 2023; RRR: ‘Sulfur Microbial Diet’ | ▼ | | ▼ | | ▼ | | | | | | | ▲ P | | | | | | ▲ | ▼ | | | | ▲ | | | | ▼
Livingstone, 2022; a priori: HDS | ▲ | | ▲ | V | | LN | | | | ▲ | | ▼ RP | M | | | | | AS | ▼ | ◀ | ▼ | ▼ | | | | ▲ ▲ | ◀ ◀
Livingstone, 2022; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF: SF | | UF: SF | ◀
Livingstone, 2022; a priori: RFS, m | ▲ ▲ ▲ | ▲ ▲ | ▲ | ▲ ▲ ▲ | ▲ ▲ ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | | ▲ | | | ▲ | | | | | | ▼
Livingstone, 2022-B; RRR: ‘DP1’ | ▼ | | | ▼ | | | | | ▲ | | | | | | | ▼ | | | ▲
Livingstone, 2022-B; RRR: ‘DP2’ | ▲ | | | ▲ | | | | ▲ | ▲ | | | | | ▼ | | | ▼ ch | | | | | ▼
Livingstone, 2022-B; RRR: ‘DP3’ | ▲ | | | | | | | ▼ | | | | | | | | | ▲ | | | | | ▲ | ▼
Maskarinec, 2017; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Maskarinec, 2017; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF: SF | | UF: SF | ◀
Maskarinec, 2017; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Maskarinec, 2017; a priori: HEI-2010 | ▲ ▲ VL | V | V | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Maskarinec, 2020; a priori: HEI-2010 | ▲ ▲ L | V | V, pro | ▲ ▲ | | | ▲ | | ▼ | ▲ pro | pro | pro | pro | | ▲ | | | AS | ▼ | ▲ | | ▼ | | ▼
Mattei, 2017; a priori: AHA-ds | ▲ ▲ | | | V | V | | ▲ | | | ▲ | | | | | | | | ▼ | SB | | ▼ | ▼ | ◀ | ▼
Mattei, 2017; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Mattei, 2017; a priori: DASHs, m | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | ▲ | D | D | ▼ | | | | | | ▼
Mattei, 2017; a priori: HEI-2005 | ▲ | | ▲ | ▲ | | | ▲ | ▲ | G | | | ▲ | | | ▲ | | | ▼ | SB | ▲ | | ▼ | ▼ | ▼
Mattei, 2017; a priori: MDS | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF: SF | | UF: SF | ◀
Mendonca, 2016; a priori: UPF, Nova4 | | | | | SB | | | ▲ | ▲ | | | ▲ P | M, P | | ▲ | | | ▲ | | | ▲ | | | | | ▲
Mirmiran, 2015; a priori: LitMDS | ▲ | | ▲ | ▲ | | Fr | | ▲ | | ▲ | FS | ▼ RP | | | ▼ | D | D | | | ▲ oo | | | X
Mirmiran, 2015; a priori: mMDS | ▲ | | ▲ | ▲ | | ▲ | | ▲ | | ▲ | | ▼ RP | | | ▼ | D | D | | | ▲ UF: SF | | UF: SF | X
Mirmiran, 2017; a posteriori: ‘Traditional’ | ▲ ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ◀ | ▲ | ◀ | | ▲ | ▲ | | | | ▼
Mirmiran, 2017; a posteriori: ‘‘Western’ | | | | | | | ▼ | | | ▼ | | ▲ R | ▼ | ▼ | | | | ▲ | ▲ | ▲ | | | | ▲ salty food | | ▲ | ▼ V
Olstad, 2017; a priori: aADGI | ▲ | | ▲ | ▲ | | | ▲ | ▲ | | | | | ▲ L | | | ▲ | | AS | ▼ | | ▼ | ▼ | ◀ | | | ▲ | ▼
Otto, 2015; a priori: aDASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | ▲ UF | ▼ | | | ▼
Otto, 2015; a priori: aHEI | ▲ | X | ▲ soy | ▲ | | LN | | | | | | W: R | ▲ W: R | | | | | | | ▲ UF: SF | ▼ Tr | UF: SF | ◀ | | | ▲ ▲
Otto, 2015; a priori: aPDQS | ▲ ▲ ▲ ▲ | ◀ | ▲ ▲ s oy | ▲ ▲ | ◀ | ▲ | ▲ | | ◀ | ▲ | ◀ | ▼ P ▼ | ◀ | ◀ | | ▲ | ▼ | ▼ | ▼ ▼ | ▲ | ◀ | ▼ | ▲ | ▼ salty food | ▲ | ◀ ◀ ◀ ◀ ◀ | ▼ FF ▼ ▼
Perala, 2017; a priori: BSD | ▲ | X | ▲ | ▲ | | | ▲ | | | ▲ | | ▼ RP | | | | | | | | | ▲ | | ◀
Pribisalić, 2021; a priori: MDSS | ▲ | ▼ | ▼ | ▲ | | ▲ | | ▲ | | ▼ | | ▼ R | ▼ | ▼ | ▲ | D | D | | ▼ | ▲ oo | | | ▲ w
Rauber, 2021; a priori: UPF, Nova4 | | | | | SB | | | ▲ | ▲ | | | | | | | | | ▲ | ▲ | | ▲ | | | AS | | ▲
Riboldi, 2022; a priori: IFI | | | | ▼ | ▲ NS ▲ SB | ▼ | ▼ | | | | ▲ | ▲ R ▲ P ▲ ▲ | ▼ | | | | | ▲ ▲ ▲ C | | | | ▼ | ▼ w | | C, SB | ▼ | ▲ beer
Roswall, 2014; a priori: HNFI | ▲ | ▲ | | ▲ | | | ▲ | | | ▲
Roswall, 2014; a priori: rMED | ▲ | X | ▲ | ▲ | | Fr | ▲ | WG | WG | ▲ | | ▼ RP | M | | | | | | | ▲ | | | ◀
San-Cristobal, 2017; a priori: MEDAS | ▲ | | ▲ | ▲ | | ▲ | | | | ▲ | | ▼ RP | ▲ W: R | | | | | ▼ | ▼ | ▲ oo ▲ oo to cook | | ▼ | ▲ w | | | ▲
Satija, 2019; a priori: hPDI | ▲ | ▼ | ▲ | ▲ | ▼ | ▲ | ▲ | | ▼ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▼ | ▼ | ▲ VO | | ▼ | | | ▲ | ▼ AP
Satija, 2019; a priori: PDI | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | ▲ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▲ | | ▼ | | | ▲ | ▼ AP
Satija, 2019; a priori: uPDI | ▼ | ▲ | ▼ | ▼ | ▲ SB | ▼ | ▼ | | ▲ | ▼ FS | FS | ▼ | M | ▼ | ▼ | D | D | ▲ | ▲ | ▼ VO | | ▼ | | | ▼ | ▼ AP
Shakeri, 2019; a priori: EDIP | ▲ ▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | ▲ salty food | ▲ T ▲ C | ▲ | ▼ ▼ V
Steffen, 2014; a priori: mMDS | ▲ | | ▲ | ▲ | ▲ FV | ▲ | ▲ | | ▼ | ▲ | | ▼ RP | | | ▼ | D | D | ▼ | | ▲ UF: SF | | UF: SF | ◀ | | ▲ CT | ▼ ▼
Sweetman, 2023; RRR: DP | ▼ | | | ▼ | | | ▼ | | ▲ | | | | | | | | | | ▲ | | | ▲ | | | | ▲
Tabung, 2019; a priori: EDIH | ▼ | ▲ FF | | ▼ | | | | | | ▲ | | ▲ R ▲ P | ▲ | ▲ | | ▲ | ▼ | ▲ | | | ▲ | | ▼ w | | ▼ C | ▲ ▲
Tabung, 2019; a priori: EDIP | ▲ ▲ | | | | ▲ | | | | ▼ | ▼ | | ▼ P ▼ R ▼ | | | | | | ▼ | | | | | | ▲ salty food | ▲ T ▲ C | ▲ | ▼ ▼ V
Tobias, 2016; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◀
Tobias, 2016; a priori: aMED | ▲ | X | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ UF:SF | | UF: SF | ◀
Tobias, 2016; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Um, 2023; a priori: DQs | ▲ | | | ▲ | ▼ | | ▲ | | ▼ | | | ▼ RP | | | | | | ▼ | | | | | | | | ▼
Vinke, 2020; a priori: LLDS | ▲ | | ▲ | ▲ | | LN | ▲ | | | ▲ | | ▼ RP | | | | ▲ | | ▼ | | ▲ | | ▼ | | | ▲
Wang, 2018 BMJ; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼
Wang, 2018 BMJ; a priori: aMED | ▲ | | ▲ | ▲ | | ▲ | ▲ | | | ▲ | | ▼ RP | | | | | | | | ▲ | | ▼ | ◀
Wang, 2018 BMJ; a priori: DASHs | ▲ | X | ▲ | ▲ | Fr | LN | ▲ | | | | | ▼ RP | | | | ▲ | | ▼ | | | | | | ▼
Winkvist, 2017; a priori: HDS | ▲ | ▼ fried | | ▲ | X | | ▲ | | | ▲ | | ▼ | | | | | | ▼ | ▼
Xu, 2021; a priori: ADG score | ▲ | | | ▲ | | | | ▲ | | | ▲ | | ▲ | | ▲ | | | | | | | | ▼ 10+/wk
Yang, 2022; a priori: aHEI-2010 | ▲ | X | ▲ | ▲ | SB | LN | ▲ | | | | | ▼ RP | | | | | | ▼ | | ▲ ▲ | ▼ Tr | | ◀ | ▼