# Appendix 5 Excluded articles

The following table lists the 1,298 full-text articles excluded after full-text screening for this systematic review question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

The existing systematic evidence scan for this question in adults and older adults included 54 articles. However, after applying the inclusion and exclusion criteria established for the update to that review, 41 remained eligible for inclusion. The following articles were excluded from the existing systematic review (rationale):

- Babio N, Toledo E, Estruch R, Mediterranean diets and metabolic syndrome status in the PREDIMED randomized trial. CMAJ. 2014;186(17):E649–657. doi:10.1503/cmaj.140764. (Data Overlap)25316904
- Casas R, Sacanella E, Urpi-Sarda M, Long-term immunomodulatory effects of a Mediterranean diet in adults at high risk of cardiovascular disease in the PREvencion con DIeta MEDiterranea (PREDIMED) randomized controlled trial. J Nutr. 2016;146(9):1684–1693. doi:10.3945/jn.115.229476. (Data Overlap)27440261
- Casas R, Sacanella E, Urpi-Sarda M, The effects of the Mediterranean diet on biomarkers of vascular wall inflammation and plaque vulnerability in subjects with high risk for cardiovascular disease. A randomized trial. PLoS One. 2014;9(6):e100084. doi:10.1371/journal.pone.0100084. (Data Overlap)24925270
- Czekajlo A, Rozanska D, Zatonska K, Szuba A, Regulska-Ilow B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. Eur J Public Health. 2019;29(2):335–340. doi:10.1093/eurpub/cky207. (study design)30285088
- Daly RM, O'Connell SL, Mundell NL, Grimes CA, Dunstan DW, Nowson CA. Protein-enriched diet, with the use of lean red meat, combined with progressive resistance training enhances lean tissue mass and muscle strength and reduces circulating IL-6 concentrations in elderly women: a cluster randomized controlled trial. Am J Clin Nutr. 2014;99(4):899–910. doi:10.3945/ajcn.113.064154. (study design)24477043
- Davis CR, Hodgson JM, Woodman R, Bryan J, Wilson C, Murphy KJ. A Mediterranean diet lowers blood pressure and improves endothelial function: results from the MedLey randomized intervention trial. Am J Clin Nutr. 2017;105(6):1305–1313. doi:10.3945/ajcn.116.146803. (Data Overlap)28424187
- Eguaras S, Toledo E, Buil-Cosiales P, Does the Mediterranean diet counteract the adverse effects of abdominal adiposity? Nutr Metab Cardiovasc Dis. 2015;25(6):569–574. doi:10.1016/j.numecd.2015.03.001. (study design)25921850
- Eguaras S, Toledo E, Hernandez-Hernandez A, Cervantes S, Martinez-Gonzalez MA. Better adherence to the Mediterranean diet could mitigate the adverse consequences of obesity on cardiovascular disease: the SUN Prospective Cohort. Nutrients. 2015;7(11):9154–9162. doi:10.3390/nu7115457. (study design)26556370
- Gardner CD, Trepanowski JF, Del Gobbo LC, Effect of low-fat vs low-carbohydrate diet on 12-month weight loss in overweight adults and the association with genotype pattern or insulin secretion: the DIETFITS randomized clinical trial. JAMA. 2018;319(7):667–679. doi:10.1001/jama.2018.0245. (study design)29466592
- Hruby A, Jacques PF. Dietary protein and changes in markers of cardiometabolic health across 20 years of follow-up in middle-aged Americans. Public Health Nutr. 2018;21(16):2998–3010. doi:10.1017/s1368980018001854. (study design)30115136
- Kafeshani M, Janghorbani M, Salehi R, Kazemi M, Entezari MH. Dietary Approaches to Stop Hypertension influence on insulin receptor substrate-1gene expression: a randomized controlled clinical trial. J Res Med Sci. 2015;20(9):832–837. doi:10.4103/1735-1995.170596. (study design)26759568

Table A 8 List of excluded articles with rationale.

Number | Citation | Rationale
1 | Abaj F, Mirzababaei A, Hosseininasab D, Bahrampour N, Clark CCT, Mirzaei K. Interactions between Caveolin-1 polymorphism and Plant-based dietary index on metabolic and inflammatory markers among women with obesity. Sci Rep. May 31 2022;12(1):9088. doi: 10.1038/S41598-022-12913-y 35641515 | Study design
2 | Abdelbasset WK, Nambi G, Alsubaie SF, A Low-Fat Diet Combined with Moderate-Intensity Aerobic Exercise is More Effective than a Low-Fat Diet or Aerobic Exercise Alone on Dyslipidemia and Depression Status in Obese Patients: A Randomized Controlled Trial. Endocr Metab Immune Disord Drug Targets. Apr 6 2021;21(12):2289–2295. doi:10.2174/1871530321666210406161226 33823782 | Intervention or Exposure; Duration of Intervention
3 | Abdou RM, El Hawary GS, Saab AA. Effect of gestational Mediterranean diet intervention on newborn fat mass and cord blood leptin level. Article. Egyptian Pediatric Association Gazette. 2020;68(1) | Country
4 | Abubakari A, Asumah MN, Abdulai NZ. Effect of maternal dietary habits and gestational weight gain on birth weight: an analytical cross-sectional study among pregnant women in the Tamale Metropolis. Article. Pan Afr Med J. 2023;44:19. doi: 10.11604/pamj.2023.44.19.38036 37013206 | Study design; Country
5 | Adam LM, Jarman M, Barker M, Manca DP, Lawrence W, Bell RC. Use of healthy conversation skills to promote healthy diets, physical activity and gestational weight gain: Results from a pilot randomised controlled trial. Patient Educ Couns. Jun 2020;103(6):1134–1142. doi:10.1016/j.pec.2020.01.001 32035738 | Comparator
6 | Adams EL, Caccavale LJ, LaRose JG, Raynor HA, Bean MK. Home Food Environment Changes and Dietary Intake during an Adolescent Behavioral Weight Loss Intervention Differ by Food Security Status. Article. Nutrients. Feb 25 2022;14(5)doi:10.3390/nu14050976 | Intervention or Exposure; Outcome; Comparator
7 | Afolabi HA, Zakariya ZB, Ahmed Shokri A, A prospective study on the relationship between frequency of food intake and the risk of obesity among patients visiting husm. Article. Obesity Medicine. 2020; 18 | Study design
8 | Agbozo F, Abubakari A, Der J, Jahn A. Maternal Dietary Intakes, Red Blood Cell Indices and Risk for Anemia in the First, Second and Third Trimesters of Pregnancy and at Predelivery. Nutrients. Mar 15 2020;12(3)doi:10.3390/nu12030777 | Outcome; Country
9 | Aghayan M, Hosseinpour-Niazi S, Bakhshi B, Mirmiran P, Azizi F. Trends in dietary food groups and Dietary Approach to Stop Hypertension (DASH) score among adults: A longitudinal study from the Tehran Lipid and Glucose Study, 2006–2017. Nutrition. Sep 2021;89:111284. doi:10.1016/j.nut.2021.111284 34090213 | Outcome
10 | Agnoli C, Sieri S, Ricceri F, Macronutrient composition of the diet and long-term changes in weight and waist circumference in the EPIC-ltaly cohort. Nutr Metab Cardiovasc Dis. Jan 4 2021;31(1):67–75. doi:10.1016/j.numecd.2020.08.007 33097407 | Intervention or Exposure
11 | Agostinis-Sobrinho C, Kievisiene J, Dubey V, Cardiovascular health behavior and blood pressure in adolescents: A longitudinal analysis. Nutr Metab Cardiovasc Dis. Jul 2022;32(7):1766–1773. doi:10.1016/j.numecd.2022.04.009 35599087 | Outcome; Comparator
12 | Aguiar-Bloemer AC, Japur CC, Francisco LV, Diez-Garcia RW. Dietary quality differences between women with and without weight loss in nutritional treatment. Clin Nutr ESPEN. Dec 2019;34:110–115. doi:10.1016/j.clnesp.2019.08.003 31677700 | Intervention or Exposure; Outcome; Comparator
13 | Ahmad S, Moorthy MV, Dernier OV, Assessment of Risk Factors and Biomarkers Associated With Risk of Cardiovascular Disease Among Women Consuming a Mediterranean Diet. Article. JAMA Netw Open. Dec 7 2018;1(8):e185708. doi:10.1001/jamanetworkopen.2018.5708 30646282 | Outcome
14 | Ainscough KM, Kennelly MA, Lindsay KL, An observational analysis of meal patterns in overweight and obese pregnancy: exploring meal pattern behaviours and the association with maternal and fetal health measures. Ir J Med Sci. May 2020;189(2):585–594. doi: 10.1007/s11845-019-02099-0 31732868 | Intervention or Exposure
15 | Ainscough KM, O'Brien EC, Lindsay KL, Nutrition, Behavior Change and Physical Activity Outcomes From the PEARS RCT-An mHealth-Supported, Lifestyle Intervention Among Pregnant Women With Overweight and Obesity. Front Endocrinol (Lausanne). 2019; 10:938. doi: 10.3389/fendo.2019.00938 32117047 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
16 | Ait-Hadad W, Bedard A, Chanoine S, Healthy diet associated with better asthma outcomes in elderly women of the French Asthma-E3N study. Eur J Nutr. Aug 2022;61(5):2555–2569. doi:10.1007/s00394-022-02815-0 35220443 | Study design; Outcome
17 | Ait-Hadad W, Bedard A, Delvert R, Plant-Based Diets and the Incidence of Asthma Symptoms among Elderly Women, and the Mediating Role of Body Mass Index. Nutrients. Dec 22 2022;15(1)doi:10.3390/nu15010052 | Outcome
18 | Aittola K, Karhunen L, Mannikko R, Enhanced Eating Competence Is Associated with Improved Diet Quality and Cardiometabolic Profile in Finnish Adults with Increased Risk of Type 2 Diabetes. Article. Nutrients. Nov 11 2021;13(11)doi:10.3390/nu13114030 | Intervention or Exposure
19 | Aji AS, Lipoeto Nl, Yusrawati Y, Association between pre-pregnancy body mass index and gestational weight gain on pregnancy outcomes: a cohort study in Indonesian pregnant women. BMC Pregnancy Childbirth. Jun 15 2022;22(1):492. doi:10.1186/s12884-022-04815-8 35705902 | Intervention or Exposure
20 | Akbari-Sedigh A, Asghari G, Yuzbashian E, Dehghan P, Imani H, Mirmiran P. Association of dietary pattern with carotid intima media thickness among children with overweight or obesity. Article. Diabetol Metab Syndr. Sep 11 2019; 11(1 ):77. doi: 10.1186/s13098-019-0472-4 31528207 | Study design
21 | Akkartal S, Gezer C. Is Nutrition Knowledge Related to Diet Quality and Obesity? Ecol Food Nutr. Mar-Apr 2020;59(2):119–129. doi: 10.1080/03670244.2019.1675654 31590573 | Study design
22 | Al Aamri KS, Alrawahi AH, Al Busaidi N, The effect of low-carbohydrate ketogenic diet in the management of obesity compared with low caloric, low-fat diet. Article in Press. Clin Nutr ESPEN. Jun 2022;49:522–528. doi:10.1016/j.clnesp.2022.02.110 | Intervention or Exposure - Foods/Beverages Not Reported
23 | Al Abdrabalnabi A, Rajaram S, Bitok E, Effects of Supplementing the Usual Diet with a Daily Dose of Walnuts for Two Years c Metabolic Syndrome and Its Components in an Elderly Cohort. Journal: Article. Nutrients. Feb 11 2020;12(2)doi:10.3390/nu12020451 | Intervention or Exposure
24 | Alae-Carew C, Scheelbeek P, Carrillo-Larco RM, Bernabe-Ortiz A, Checkley W, Miranda JJ. Analysis of dietary patterns and cross-sectional and longitudinal associations with hypertension, high BMI and type 2 diabetes in Peru. Public Health Nutr. Apr 2020;23(6):1009–1019. doi:10.1017/S1368980019002313 31456536 | Size or Power
25 | Alaghehband FR, Erkkila AT, Rikkonen T, Sirola J, Kroger H, Isanejad M. Association of Baltic Sea and Mediterranean diets with frailty phenotype in older women, Kuopio OSTPRE-FPS study. Eur J Nutr. Mar 2021;60(2):821–831. doi:10.1007/s00394-020-022905 32462318 | Study design; Outcome
26 | Alamolhoda SH, Simbar M, Mirmiran P, Mirabi P. Effect of low trans-fatty acid intakes on preeclampsia: A randomized controlled trial. Article. J Res Med Sci. 2020;25(1):112. doi:10.4103/jrms.JRMS_149_19 33912222 | Intervention or Exposure
27 | Albert SL, Massar RE, Correa L, Change in cardiometabolic risk factors in a pilot safety-net plant-based lifestyle medicine program. Front Nutr. 2023;10:1155817. doi:10.3389/fnut.2023.1155817 37153909 | Intervention or Exposure - Foods/Beverages Not Reported
28 | Alexandrou C, Henriksson H, Henstrom M, Effectiveness of a Smartphone App (MINISTOP 2.0) integrated in primary child health care to promote healthy diet and physical activity behaviors and prevent obesity in preschool-aged children: randomized controlled trial. Int J Behav Nutr Phys Act. Feb 21 2023;20(1):22. doi:10.1186/s12966-023-01405-5 36810069 | Intervention or Exposure
29 | Aljefree NM, Almoraie NM, Shatwan IM. Association of two types of dietary pattern scores with cardiovascular disease risk factors and serum 25 hydroxy vitamin D levels in Saudi Arabia. Food Nutr Res. 2021;65doi: 10.29219/fnr.v65.5481 | Study design
30 | Aller EE, van Baak MA. Evaluation of an 18-month commercial multidisciplinary obesity treatment programme. Article. Clin Obes. Feb 2016;6(1):33–41. doi:10.1111/cob.12122 26573718 | Study design; Publication status
31 | Aller R, Izaola O, Primo D, de Luis DA. The effect of single-nucleotide polymorphisms at the ADIPOQ gene locus rs1501299 on metabolic parameters after 9 mo of a high-protein/low-carbohydrate versus a standard hypocaloric diet. Journal Article; Randomized Controlled Trial. Nutrition. Sep 2019;65:44–49. doi: 10.1016/j.nut.2019.02.012 31029921 | Intervention or Exposure - Foods/Beverages Not Reported
32 | Almanza-Aguilera E, Hernaez A, Corella D, Transcriptional response to a Mediterranean diet intervention exerts a modulatory effect on neuroinflammation signaling pathway. Article. Nutr Neurosci. Feb 2022;25(2):256–265. doi: 10.1080/1028415X.2020.1749334 32290787 | Size or Power
33 | Al-Nimr Rl, Wright KCS, Aquila CL, Petersen CL, Gooding TL, Batsis JA. Intensive nutrition counseling as part of a multi-component weight loss intervention improves diet quality and anthropometries in older adults with obesity. Clin Nutr ESPEN. 2020;40doi:10.1016/j.clnesp.2020.09.00 | Study design
34 | Alonso-Bernaldez M, Palou-March A, Zamanillo-Campos R, Palou A, Palou M, Serra F. A Diet Profiling Algorithm (DPA) to Rank Diet Quality Suitable to Implement in Digital Tools-A Test Study in a Cohort of Lactating Women.. . .15:. | Study design; Outcome
35 | Amani R, Parohan M, Jomehzadeh N, Haghighizadeh MH. Dietary and Biochemical Characteristics Associated with Normal-Weight Obesity. Int J Vitam Nutr Res. Nov 2019;89(5–6):331–336. doi:10.1024/0300-9831/a000477 30856081 | Study design
36 | Amerikanou C, Kleftaki SA, Valsamidou E, Tzavara C, Gioxari A, Kaliora AC. Dietary Patterns, Cardiometabolic and Lifestyle Variables in Greeks with Obesity and Metabolic Disorders. Nutrients. Nov 28 2022;14(23)doi:10.3390/nu14235064 | Study design
37 | Amil S, Lemieux I, Poirier P, Lamarche B, Despres JP, Almeras N. Targeting Diet Quality at the Workplace: Influence on Cardiometabolic Risk. Nutrients. Jun 30 2021;13(7)doi:10.3390/nu13072283 | Study design; Comparator
38 | Aminianfar A, Soltani S, Hajianfar H, Azadbakht L, Shahshahan Z, Esmaillzadeh A. The association between dietary glycemic index and load and risk of gestational diabetes mellitus: A prospective study. Diabetes Res Clin Pract. Dec 2020;170:108469. doi: 10.1016/j.diabres.2020.108469 32987041 | Intervention or Exposure
39 | Amoah S, Ennin R, Sagoe K, Feasibility of a Culturally Adapted Dietary Weight-Loss Intervention among Ghanaian Migrants in Berlin, Germany: The ADAPT Study. Int J Environ Res Public Health. Jan 9 2021;18(2)doi:10.3390/ijerph18020510 | Study design; Comparator
40 | Anand C, Kranz RM, Husain S, Bridging the gap between science and society: long-term effects of the Healthy Lifestyle Community Programme (HLCP, cohort 1) on weight and the metabolic risk profile: a controlled study. BMJ Nutr Prev Health. 2022;5(1):44–54. doi:10.1136/bmjnph-2021-000340 | Duration of Intervention; Comparator
41 | Anand SS, Gupta M, Teo KK, Causes and consequences of gestational diabetes in South Asians living in Canada: results from a prospective cohort study. Article. CMAJ Open. Aug 9 2017;5(3):E604–E611. doi:10.9778/cmajo.20170027 | Outcome
42 | Ancira-Moreno M, O'Neill MS, Rivera-Dommarco JA, Dietary patterns and diet quality during pregnancy and low birthweight: The PRINCESA cohort. Matern Child Nutr. Jul 2020;16(3):e12972. doi:10.1111/mcn.12972 32037674 | Outcome
43 | Ancira-Moreno M, Vadillo-Ortega F, Rivera-Dommarco JA, Gestational weight gain trajectories over pregnancy and their association with maternal diet quality: Results from the PRINCESA cohort. Article. Nutrition. Sep 2019;65:158–166. doi: 10.1016/j.nut.2019.02.002 31132630 | Data overlap
44 | Andersen E, van der Ploeg HP, van Mechelen W, Contributions of changes in physical activity, sedentary time, diet and body weight to changes in cardiometabolic risk. Int J Behav Nutr Phys Act. Dec 20 2021; 18(1): 166. doi: 10.1186/s12966-021-01237-1 34930299 | Intervention or Exposure
45 | Andrade MEdC, Lyra CdO, AraUJo FRd, Bagni UV. Influence of federal feeding programs on the anthropometric indicators of nutritional status of adolescents. Article. Revista de Nutrigao. 2022;35doi: 10.1590/1678-9865202235e210046 | Intervention or Exposure
46 | Andre P, Proctor G, Driollet B, The role of overweight in the association between the Mediterranean diet and the risk of type 2 diabetes mellitus: a mediation analysis among 21 585 UK biobank participants. Int J Epidemiol. Oct 1 2020;49(5):1582–1590. doi:10.1093/ije/dyaa103 32754745 | Outcome
47 | Andueza N, Martin-Calvo N, Navas-Carretero S, Cuervo M. The ALINFA Intervention Improves Diet Quality and Nutritional Status in Children 6 to 12 Years Old. Nutrients. May 18 2023;15(10)doi:10.3390/nu15102375 | Duration of Intervention
48 | Angali KA, Shahri P, Borazjani F. Maternal dietary pattern in early pregnancy is associated with gestational weight gain and hyperglycemia: A cohort study in South West of Iran. Diabetes Metab Syndr. Nov-Dec 2020; 14(6): 1711–1717. doi:10.1016/j.dsx.2020.08.008 32916554 | Outcome
49 | Anleu E, Reyes M, Araya BM, Flores M, Uauy R, Garmendia ML. Effectiveness of an Intervention of Dietary Counseling for Overweight and Obese Pregnant Women in the Consumption of Sugars and Energy. Journal Article; Randomized Controlled Trial. Nutrients. Feb 13 2019;11(2)doi:10.3390/nu11020385 | Intervention or Exposure
50 | Aparecida Silveira E, Danesio de Souza J, Dos Santos Rodrigues AP, Lima RM, de Souza Cardoso CK, de Oliveira C. Effects of Extra Virgin Olive Oil (EVOO) and the Traditional Brazilian Diet on Sarcopenia in Severe Obesity: A Randomized Clinical Trial. Journal Article; Randomized Controlled Trial. Nutrients. May 21 2020;12(5)doi:10.3390/nu12051498 | Intervention or Exposure - Foods/Beverages Not Reported
51 | Arapaki A, Paltoglou G, Ziogou G, 185 The effect of dietary patterns on excessive gestational weight gain in a sample of greek women. European Journal of Obstetrics & Gynecology & Reproductive Biology. 2022;270:N.PAG–N.PAG. | Publication status
52 | Ard JD, Lewis KH, Rothberg A, Effectiveness of a Total Meal Replacement Program (OPTIFAST Program) on Weight Loss: Results from the OPTIWIN Study. Article. Obesity (Silver Spring). Jan 2019;27(1):22–29. doi:10.1002/oby.22303 30421863 | Intervention or Exposure
53 | Arjmand G, Abbas-Zadeh M, Eftekhari MH. Effect of MIND diet intervention on cognitive performance and brain structure in healthy obese women: a randomized controlled trial. Sci Rep. Feb 21 2022;12(1):2871. doi: 10.1038/s41598-021-04258-9 35190536 | Outcome
54 | Aronica L, Rigdon J, Offringa LC, Stefanick ML, Gardner CD. Examining differences between overweight women and men in 12-month weight loss study comparing healthy low-carbohydrate vs. low-fat diets. Int J Obes (Lond). Jan 2021;45(1):225–234. doi: 10.1038/S41366-020-00708-y 33188301 | Intervention or Exposure
55 | Arredondo A, Torres C, Orozco E, Socio-economic indicators, dietary patterns, and physical activity as determinants of maternal obesity in middle-income countries: Evidences from a cohort study in Mexico. Article. Int J Health Plann Manage. Jan 2019;34(1):e713–e725. doi:10.1002/hpm.2684 30350426 | Study design
56 | Arslanian KJ, Fidow UT, Atanoa T, Effect of maternal nutrient intake during 31–37 weeks gestation on offspring body composition in Samoa. Ann Hum Biol. Dec 2020;47(7–8):587–596. doi:10.1080/03014460.2020.1820078 32892647 | Intervention or Exposure; Outcome
57 | Arvizu M, Afeiche MC, Hansen S, Halldorsson TF, Olsen SF, Chavarro JE. Fat intake during pregnancy and risk of preeclampsia: a prospective cohort study in Denmark. Article. Eur J Clin Nutr. Jul 2019;73(7):1040–1048. doi:10.1038/s41430-018-0290-z 30194370 | Intervention or Exposure; Outcome
58 | Asano M, Kushida M, Yamamoto K, Tomata Y, Tsuji I, Tsuduki T. Abdominal Fat in Individuals with Overweight Reduced by Consumption of a 1975 Japanese Diet: A Randomized Controlled Trial. Historical Article; Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Obesity (Silver Spring). Jun 2019;27(6):899–907. doi:10.1002/oby.22448 30985996 | Duration of Intervention
59 | Ashwin D, Gibson L, Hagemann E, D'Vaz N, Bear N, Silva D. The impact a Mediterranean Diet in the third trimester of pregnancy has on neonatal body fat percentage. J Dev Orig Health Dis. Aug 2022;13(4):500–507. doi:10.1017/S2040174421000556 34658323 | Outcome
60 | Assaf-Balut C, Garcia De La Torre N, Bordiu E, Consumption of fat-free dairy products is not associated with a lower risk of maternofetal adverse events. Article. BMJ Open Diabetes Research and Care. 2020;8(1) | Intervention or Exposure; Outcome
61 | Assaf-Balut C, Garcia de la Torre N, Duran A, An Early, Universal Mediterranean Diet-Based Intervention in Pregnancy Reduces Cardiovascular Risk Factors in the "Fourth Trimester". Article. J Clin Med. Sep 19 2019;8(9)doi:10.3390/jcm8091499 | Study design
62 | Assaf-Balut C, Garcia de la Torre N, Fuentes M, A High Adherence to Six Food Targets of the Mediterranean Diet in the Late First Trimester is Associated with a Reduction in the Risk of Materno-Foetal Outcomes: The St. Carlos Gestational Diabetes Mellitus Prevention Study. Article. Nutrients. Dec 31 2018;11(1)doi:10.3390/nu11010066 | Study design; Outcome
63 | Astuti T, Marbun R, Surmita. The Effectiveness of Nutrition Education, Counseling and Exercise on Desirable Dietary Pattern Score and Weight Loss in Obese Teenagers. Journal: Conference Abstract. Annals of Nutrition and Metabolism. 2019;75(3):367–368. | Publication status
64 | Atakora L, Poston L, Hayes L, Flynn AC, White SL. Influence of GDM Diagnosis and Treatment on Weight Gain, Dietary Intake and Physical Activity in Pregnant Women with Obesity: Secondary Analysis of the UPBEAT Study. Nutrients. Jan 30 2020;12(2)doi:10.3390/nu12020359 | Intervention or Exposure
65 | Atar FA, Verep S. Dietary advices for patients with metabolic syndrome and obesity. World J Urol. May 2023;41(5):1211–1214. doi: 10.1007/S00345-022-04250-6 36625919 | Study design
66 | Atkinson SA, Maran A, Dempsey K, Be Healthy in Pregnancy (BHIP): A Randomized Controlled Trial of Nutrition and Exercise Intervention from Early Pregnancy to Achieve Recommended Gestational Weight Gain. Article. Nutrients. Feb 15 2022;14(4)doi:10.3390/nu14040810 | Intervention or Exposure - Foods/Beverages Not Reported
67 | Author N/A. To study the role of whole food, plant based diet in reducing weight in obese patients in comparison with the standard weight reducing diet, http://www.who.int/trialsearch/Trial2.aspx?TriallD=CTRI/2020/08/027057. 2020. | Publication status
68 | Author N/A. A quasi-experimental study of a health educational intervention targeting parents of overweight and obese pre-school children in Shanghai, China. Obesity reviews. 2020. 21:. | Publication status
69 | Author N/A. Assessing compliance with Paleolithic diet by calculating Paleolithic Diet Fraction as the fraction of intake from Paleolithic food groups. Journal: Article. Clinical nutrition experimental. 2019;25:29–35. | Health Status- 100% CVD
70 | Author N/A. Diet for the Maintenance of Weight Loss and Metabolic Health in Obese Postmenopausal Women. https://clinicaltrialsgov/show/NCT04136093. 2019 | Publication status
71 | Author N/A. Gut microbiota shift and low fibre intake in post gestational diabetes women. Journal: Conference Abstract. Gut. 2019;68:A96-. | Publication status
72 | Author N/A. Low Carbohydrate Diet Versus Low Fat Diet in Reversing the Metabolic Syndrome Using NCEP ATP III Criteria. https://clinicaltrialsgov/show/NCT04681924. 2020 | Country; Publication status
73 | Author N/A. Quality of Diet in Preschool Population. https://clinicaltrialsgov/show/NCT04301180. 2020 | Publication status
74 | Author N/A. Randomized Controlled Multi-center Study of the New Nordic Diet in Gestational Diabetes Mellitus. https://clinicaltrialsgov/show/NCT04169243. 2019 | Study design; Publication status
75 | Author N/A. Retraction and republication—Effect of a high-fat Mediterranean diet on bodyweight and waist circumference: a prespecified secondary outcomes analysis of the PREDIMED randomised controlled trial (The Lancet Diabetes & Endocrinology (2016) 4(8) (666–676)(S2213858716300857)(10.1016/S2213–8587(16)30085–7). Journal: Erratum. The lancet diabetes and endocrinology. 2019;7(5):334-. | Publication status
76 | Author N/A. The development, implementation and evaluation of a weight loss intervention for overweight/obese primary school educators at selected schools within the Metro North District in Western Cape Province, South Africa: a randomized controlled trial. http://wwwwhoint/trialsearch/Trial2aspx?TrialID=PACTR201910535635886. 2019; | Publication status
77 | Author N/A. The Effect of Lifestyle Intervention for Hypertriglyceridemia on the Pathogenesis of Adverse Pregnancy Outcome. https://clinicaltrialsgov/show/NCT04275622. 2020 | Publication status
78 | Author N/A. The Effect of the DASH Diet Containing Meat on Muscle and Metabolic Health in Older Adults. https://clinicaltrialsgov/show/NCT04127240. 2019 | Publication status
79 | Author N/A. Traditional Korean diet can alter the urine organic acid profile, which may reflect the metabolic influence of the diet. Research Article. J nutr health. 2020;53(3):231–243. | Duration of Intervention; Language
80 | Author N/A. Vegetarian Kids Shown to Have Similar Growth, Nutrition vs Those Who Eat Meat. Today's Dietitian. 2022;24(5):53–53. | Publication status
81 | Autoren Pletsch-Borba L, Wernicke C, Apostoloupoulou K, Determinants of adherence to a high-protein and high-unsaturated fatty acids dietary intervention: 1-year results of the NutriAct randomized controlled multi-center trial. Journal: Conference Abstract. Diabetologie und stoffwechsel. 2021;16(SUPPL 1):S83–S84. | Publication status
82 | Avnon T, Paz Dubinsky E, Lavie I, Ben-Mayor Bashi T, Anbar R, Yogev Y. The impact of a vegan diet on pregnancy outcomes. J Perinatol. May 2021;41(5):1129–1133. doi:10.1038/s41372-020-00804-x 32873905 | Outcome
83 | Aziz S, Rehman H. Mechanism and benefits of ketogenic diet for weight loss and health. Article. Rawal Medical Journal. 2019;44(4):880–883. | Study design
84 | Azrak MA, Fasano MV, Avico AJ, Prolonged body weight gain, lifestyle changes and health-related quality of life in children during the COVID-19 pandemic lockdown: A follow-up study. Article. Eur J Clin Nutr. Apr 2023;77(4):460–467. doi:10.1038/s41430-022-01252-w 36510000 | Intervention or Exposure
85 | Babili MG, Amerikanou C, Papada E, Christopoulos G, Tzavara C, Kaliora AC. The effect of prenatal maternal physical activity and lifestyle in perinatal outcome: results from a Greek study. Eur J Public Health. Apr 1 2020;30(2):328–332. doi:10.1093/eurpub/ckz223 31860072 | Outcome
86 | Baden MY, Satija A, Hu FB, Huang T. Change in Plant-Based Diet Quality Is Associated with Changes in Plasma Adiposity-Associated Biomarker Concentrations in Women. Journal: Article. J Nutr. Apr 1 2019;149(4):676–686. doi:10.1093/jn/nxy301 30927000 | Outcome
87 | Badr HE, Saunders T, Carter A, Reyes Castillo L, Bayoumy O, Barrett M. Impact of Lifestyle Modification on Quality of Life in Patients with Metabolic Syndrome: Findings from the CHANGE Program Intervention Study in Prince Edward Island, Canada. Metab Syndr Relat Disord. Nov 2022;20(9):532–542. doi:10.1089/met.2022.0056 36037016 | Study design; Intervention or Exposure
88 | Bakirhan H, Pehlivan M, Ozyurek F, Ozkaya V, Yousefirad N. Diet, Sleep and Depression: Does Adherence to the Mediterranean Diet Matter? Article. Journal of Turkish Sleep Medicine. 2022;9(2):172–179. doi:10.4274/jtsm.galenos.2022.15046 | Study design; Outcome
89 | Bansal S, Connolly M, Harder T. Impact of a Whole-Foods, Plant-Based Nutrition Intervention on Patients Living with Chronic Disease in an Underserved Community. Am J Lifestyle Med. May-Jun 2022;16(3):382–389. doi: 10.1177/15598276211018159 35706591 | Study design
90 | Barbosa C, Costa A, Hetherington MM, Oliveira A. Association of early feeding practices with dietary patterns of 7-year-olds from the birth cohort Generation XXL Appetite. Apr 1 2022;171:105909. doi:10.1016/j.appet.2021.105909 | Outcome
91 | Barchitta M, Magnano San Lio R, La Rosa MC, The Effect of Maternal Dietary Patterns on Birth Weight for Gestational Age: Findings from the MAMI-MED Cohort. Nutrients. Apr 16 2023;15(8)doi:10.3390/nu15081922 | Did not account for at least 1 key confounder
92 | Barker K, Davy B. Is Consumption of Ultra-Processed Foods Associated with Cardiometabolic Risk? Scan's Pulse. Winter2021 2021;41(1):1–5. | Publication status
93 | Barnaba L, Intorre F, Azzini E, Evaluation of adherence to Mediterranean diet and association with clinical and biological markers in an Italian population. Nutrition. Sep 2020;77:110813. doi:10.1016/j.nut.2020.110813 32450332 | Study design; Outcome
94 | Barnard ND, Alwarith J, Rembert E, A Mediterranean Diet and Low-Fat Vegan Diet to Improve Body Weight and Cardiometabolic Risk Factors: A Randomized, Cross-over Trial. J Am Nutr Assoc. Feb 2022;41(2):127–139. doi: 10.1080/07315724.2020.1869625 33544066 | Intervention or Exposure - Foods/Beverages Not Reported
95 | Barrea L, Muscogiuri G, Savastano S, Colao A, Project OP. Cut-off for the Mediterranean diet score to identify subjects with morning chronotype in middle-aged Italian adults. Article. Minerva Endocrinol (Torino). Mar 2022;47(1):129–131. doi:10.23736/S2724-6507.21.03411-8 33855385 | Publication status
96 | Barrea L, Muscogiuri G, Savastano S, Colao A, Project OP. What about Mediterranean diet as tool to improve sleep quality in obesity? Minerva Endocrinol (Torino). Jun 2022;47(2):253–255. doi:10.23736/S2724-6507.21.03410-6 33855384 | Publication status
97 | Barreto J, Assis AMO, de Santana MLP, Pitangueira JCD, Cunha CM, Costa PRF. Influence of sugar consumption from foods with different degrees of processing on anthropometric indicators of children and adolescents after 18 months of follow-up. Br J Nutr. Dec 14 2022; 128(11 ):2267–2277. doi: 10.1017/S0007114522000411 35109951 | Intervention or Exposure
98 | Barros L, Lopes C, Oliveira A. Child and family characteristics are associated with a dietary variety index in 4-year-old children from the Generation XXI cohort. Article. Nutr Res. Mar 2019;63:76–85. doi:10.1016/j.nutres.2018.12.001 30824400 | Study design
99 | Bartha V, Exner L, Schweikert D, Effect of the Mediterranean diet on gingivitis: A randomized controlled trial. J Clin Periodontol. Feb 2022;49(2):111–122. doi: 10.1111/jcpe.13576 34818686 | Duration of Intervention
100 | Basri H, Hadju V, Zulkifli A, Dietary diversity, dietary patterns and dietary intake are associated with stunted children in Jeneponto District, Indonesia. Gac Sanit. 2021;35 Suppl 2:S483–S486. doi:10.1016/j.gaceta.2021.10.077 34929881 | Intervention or Exposure; Country
101 | Basu A, Chien LC, Alman AC, Snell-Bergeon JK. Associations of dietary patterns and nutrients with coronary artery calcification and pericardial adiposity in a longitudinal study of adults with and without type 1 diabetes. Eur J Nutr. Oct 2021;60(7):3911–3925. doi: 10.1007/S00394-021-02564-6 33904996 | Outcome
102 | Basu A, Feng D, Planinic P, Ebersole JL, Lyons TJ, Alexander JM. Dietary Blueberry and Soluble Fiber Supplementation Reduces Risk of Gestational Diabetes in Women with Obesity in a Randomized Controlled Trial. Article. J Nutr. May 11 2021; 151 (5): 1128–1138. doi: 10.1093/jn/nxaa435 33693835 | Intervention or Exposure
103 | Baudry J, Pointereau P, Seconda L, Improvement of diet sustainability with increased level of organic food in the diet: findings from the BioNutriNet cohort. Article. Am J Clin Nutr. Apr 1 2019; 109(4): 1173–1188. doi:10.1093/ajcn/nqy361 30982857 | Intervention or Exposure
104 | Bayerle P, Beyer S, Tegtbur U, Exercise Capacity, Iron Status, Body Composition, and Mediterranean Diet in Patients with Chronic Heart Failure. Nutrients. Dec 21 2022;15(1)doi:10.3390/nu15010036 | Health Status- 100% CVD
105 | Beaudry KM, Ludwa IA, Thomas AM, Ward WE, Falk B, Josse AR. First-year university is associated with greater body weight, body composition and adverse dietary changes in males than females. Article. PLoS One. Jul 3 2019;14(7):e0218554. doi: 10.1371/journal.pone.0218554 31269047 | Intervention or Exposure
106 | Bedard, A.,Northstone, K.,John Henderson, A.,Shaheen, S. O.. Mediterranean diet during pregnancy and childhood respiratory and atopic outcomes: Birth cohort study. European Respiratory Journal. 2020. 55:. | Health Status
107 | Bell LK, Schammer C, Devenish G, Dietary Patterns and Risk of Obesity and Early Childhood Caries in Australian Toddlers: Findings from an Australian Cohort Study. Nutrients. Nov 19 2019; 11(11)doi:10.3390/nu11112828 | Study design
108 | Bell M, Duncan MJ, Patte KA, Roy BD, Ditor DS, Klentrou P. Changes in Body Mass, Physical Activity, and Dietary Intake during the COVID-19 Pandemic Lockdowns in Canadian University Students. Biology (Basel). Feb 17 2023;12(2)doi:10.3390/biology12020326 | Intervention or Exposure; Outcome
109 | Bellikci-Koyu E, Sarer-Yurekli BP, Karagozlu C, Aydin-Kose F, Ozgen AG, Buyuktuncer Z. Probiotic kefir consumption improves serum apolipoprotein A1 levels in metabolic syndrome patients: a randomized controlled clinical trial. Nutr Res. Jun 2022;102:59–70. doi:10.1016/j.nutres.2022.02.006 35405603 | Intervention or Exposure
110 | Bel-Serrat S, Ojeda-Rodriguez A, Heinen MM, Clustering of Multiple Energy Balance-Related Behaviors in School Children and its Association with Overweight and Obesity-WHO European Childhood Obesity Surveillance Initiative (COSI 2015(-)2017). Article. Nutrients. Feb 27 2019;11(3)doi:10.3390/nu11030511 | Study design; Intervention or Exposure
111 | Bennet L, Fawad A, Struck J, Larsson SL, Bergmann A, Melander O. The effect of a randomised controlled lifestyle intervention on weight loss and plasma proneurotensin. Article. BMC Endocr Disord. Oct 31 2022;22(1):264. doi: 10.1186/s12902-022-01183-4 36316682 | Intervention or Exposure - Foods/Beverages Not Reported
112 | Ben-Yacov O, Godneva A, Rein M, Gut microbiome modulates the effects of a personalised postprandial-targeting (PPT) diet on cardiometabolic markers: a diet intervention in pre-diabetes. Article in Press. Gut. Aug 2023;72(8):1486–1496. doi: 10.1136/gutjnl-2022-329201 37137684 | Intervention or Exposure; Outcome
113 | Ben-Yacov O, Godneva A, Rein M, Personalized Postprandial Glucose Response-Targeting Diet Versus Mediterranean Diet for Glycemic Control in Prediabetes. Diabetes Care. Sep 2021;44(9):1980–1991. doi:10.2337/dc21-0162 34301736 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
114 | Bergia RE, Giacco R, Hjorth T, Differential Glycemic Effects of Low- versus High-Glycemic Index Mediterranean-Style Eating Patterns in Adults at Risk for Type 2 Diabetes: The MEDGI-Carb Randomized Controlled Trial. Article. Nutrients. Feb 8 2022;14(3)doi:10.3390/nu14030706 | Outcome; Comparator
115 | Bernhart JA, Turner-McGrievy GM, Wilson MJ, Sentman C, Wilcox S, Rudisill C. NEW Soul in the neighborhood-reach and effectiveness of a dissemination and implementation feasibility study. Transl Behav Med. Apr 3 2023;13(3):123–131. doi: 10.1093/tbm/ibac080 36689305 | Comparator
116 | Bernhart JA, Turner-McGrievy GM, Wirth MD, Shivappa N, Hebert JR. The IMAGINE Intervention: Impacting Physical Activity, Body Fat, Body Mass Index, and Dietary Inflammatory Index. Transl J Am Coll Sports Med. Winter 2022;7(1)doi:10.1249/tjx.0000000000000181 | Study design; Intervention or Exposure; Comparator
117 | Bernier E, Plante AS, Robitaille J, First-trimester diet quality in association with maternal subcutaneous and visceral adipose tissue thicknesses and glucose homeostasis during pregnancy. Int J Food Sci Nutr. Mar 2023;74(2):268–278. doi: 10.1080/09637486.2023.2171371 36710410 | Outcome
118 | Berthy F, Brunin J, Alles B, Association between adherence to the EAT-Lancet diet and risk of cancer and cardiovascular outcomes in the prospective NutriNet-Sante cohort. Annals of Nutrition and Metabolism. Aug 2023;79:391–391. | Outcome
119 | Bethancourt HJ, Kratz M, O'Connor K. A short-term religious "fast" from animal products has a minimal impact on cardiometabolic health biomarkers irrespective of concurrent shifts in distinct plant-based food groups. Article. Am J Clin Nutr. Sep 1 2019;110(3):722–732. doi:10.1093/ajcn/nqz153 31380559 | Duration of Intervention
120 | Beunza JJ, Toledo E, Hu FB, Adherence to the Mediterranean diet, long-term weight change, and incident overweight or obesity: the Seguimiento Universidad de Navarra (SUN) cohort. Article. Am J Clin Nutr. Dec 2010;92(6):1484–93. doi: 10.3945/ajcn.2010.29764 20962161 | Data overlap
121 | Beydoun MA, Nkodo A, Fanelli-Kuczmarski MT, Longitudinal Associations between Monetary Value of the Diet, DASH Diet Score and the Allostatic Load among Middle-Aged Urban Adults. Article. Nutrients. Oct 3 2019; 11(10)doi:10.3390/nu11102360 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
122 | Bhupathiraju SN, Sawicki CM, Goon S, A healthy plant-based diet is favorably associated with cardiometabolic risk factors among participants of South Asian ancestry. Am J Clin Nutr. Oct 6 2022;116(4):1078–1090. doi:10.1093/ajcn/nqac174 35731596 | Size or Power
123 | Bhutani S, vanDellen MR, Cooper JA. Longitudinal Weight Gain and Related Risk Behaviors during the COVID-19 Pandemic in Adults in the US. Article. Nutrients. Feb 19 2021; 13(2): 1–14. doi:10.3390/nu13020671 | Intervention or Exposure
124 | Bibiloni MDM, Fernandez-Bianco J, Pujol-Plana N, [Reversion of overweight and obesity in Vilafranca del Penedes child population: ACTIVA'T Program (2012)]. Journal Article; Randomized Controlled Trial. Gac Sanit. Mar-Apr 2019;33(2):197–202. Reversion de sobrepeso y obesidad en poblacion infantil de Vilafranca del Penedes: Programa ACTIVA'T (2012). doi:10.1016/j.gaceta.2017.10.002 | Study design
125 | Biddulph C, Holmes M, Tran TD, Associations between Maternal Nutrition and the Concentrations of Human Milk Oligosaccharides in a Cohort of Healthy Australian Lactating Women. Article. Nutrients. Apr 26 2023;15(9)doi:10.3390/nu15092093 | Intervention or Exposure; Outcome
126 | Bijlholt M, Ameye L, van Uytsel H, Devlieger R, Bogaerts A. Evolution of Postpartum Weight and Body Composition after Excessive Gestational Weight Gain: The Role of Lifestyle Behaviors-Data from the INTER-ACT Control Group. Article. Int J Environ Res Public Health. Jun 11 2021;18(12)doi:10.3390/ijerph18126344 | Intervention or Exposure
127 | Black MM, Hager ER, Wang Y, Toddler obesity prevention: A two-generation randomized attention-controlled trial. Matern Child Nutr. Jan 2021;17(1):e13075. doi:10.1111/mcn.13075 32885909 | Intervention or Exposure
128 | Blancas-Sanchez IM, Del Rosal Jurado M, Aparicio-Martinez P, A Mediterranean-Diet-Based Nutritional Intervention for Children with Prediabetes in a Rural Town: A Pilot Randomized Controlled Trial. Nutrients. Sep 1 2022;14(17)doi:10.3390/nu14173614 | Size or Power
129 | Blondal BS, Geirsdottir OG, Beck AM, HOMEFOOD randomized trial-beneficial effects of 6-month nutrition therapy on body weight and physical function in older adults at risk for malnutrition after hospital discharge. Eur J Clin Nutr. Jan 2023;77(1):45–54. doi:10.1038/s41430-022-01195-2 36028775 | Intervention or Exposure - Foods/Beverages Not Reported
130 | Blumenthal JA, Smith PJ, Mabe S, Longer Term Effects of Diet and Exercise on Neurocognition: 1-Year Follow-up of the ENLIGHTEN Trial. J Am Geriatr Soc. Mar 2020;68(3):559–568. doi:10.1111/jgs.16252 31755550 | Comparator
131 | Bogataj Jontez N, Kenig S, Sik Novak K, Petelin A, Jenko Praznikar Z, Mohorko N. Habitual low carbohydrate high fat diet compared with omnivorous, vegan, and vegetarian diets. Front Nutr. 2023;10:1106153. doi:10.3389/fnut.2023.1106153 37125046 | Study design
132 | Boleslawska I, Kowalowka M, Dobrzynska M, Karazniewicz-Lada M, Przyslawski J. Differences in the Concentration of Vitamin D Metabolites in Plasma Due to the Low-Carbohydrate-High-Fat Diet and the Eastern European Diet-A Pilot Study. Nutrients. Aug 13 2021;13(8)doi:10.3390/nu13082774 | Duration of Intervention; Outcome
133 | Boonpor J, Petermann-Rocha F, Parra-Soto S, Types of diet, obesity, and incident type 2 diabetes: Findings from the UK Biobank prospective cohort study. Diabetes Obes Metab. Jul 2022;24(7):1351–1359. doi: 10.1111/dom.14711 | Outcome
134 | Boriak KR, Vesnina LE. Relationship of the Eating Behavior Features with Anthropometric Indicators and Energy Value of the Diet in Young People with Normal Weight and Overweight. Article. Wiad Lek. 2020;73(12 cz 1):2586–2590.33577473 | Study design; Intervention or Exposure
135 | Bourke S, Morton JM, Williams P. Effect of JumpstartMD, a Commercial Low-Calorie Low-Carbohydrate Physician-Supervised Weight Loss Program, on 22,407 Adults. Article. J Obes. 2020;2020:8026016. doi: 10.1155/2020/8026016 32318289 | Study design; Intervention or Exposure
136 | Boutros GH, Landry-Duval MA, Garzon M, Karelis AD. Is a vegan diet detrimental to endurance and muscle strength? Eur J Clin Nutr. Nov 2020;74(11):1550–1555. doi:10.1038/s41430-020-0639-y 32332862 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
137 | Bozbulut R, Soysal Acar AS, Doger E, Orhun Camurdan M, Bideci A. The relationship between alexithymia, health literacy, and diet quality in obese adolescents. Article. J Pediatr Endocrinol Metab. Feb 23 2023;36(2):137–146. doi:10.1515/jpem-2022-0405 36588297 | Outcome
138 | Bozkurt YE, Temeltas G, Muezzinoglu T, Ucer O. Mediterranean Diet and Overactive Bladder. Int Neurourol J. Jun 2022;26(2):129–134. doi: 10.5213/inj.2142118.059 35793991 | Study design; Outcome
139 | Bragg AE, Crowe-White KM, Ellis AC, Changes in Cardiometabolic Risk Among Older Adults with Obesity: An Ancillary Analysis of a Randomized Controlled Trial Investigating Exercise Plus Weight Maintenance and Exercise Plus Intentional Weight Loss by Caloric Restriction. J Acad Nutr Diet. Feb 2022;122(2):354–362. doi:10.1016/j.jand.2021.07.009 34486528 | Intervention or Exposure
140 | Brauchmann J, Bau AM, Mensink GBM, Dietary Patterns in Adolescent Obesity as Predictors of Long-Term Success Following an Intensive Inpatient Lifestyle Programme. Int J Environ Res Public Health. Dec 10 2022;19(24)doi:10.3390/ijerph192416613 | Intervention or Exposure
141 | Brazo Sayavera J, Crochemore-Silva I, Bizzozero Peroni B, Gonzalez-Galvez N, de Camargo EM, Lopez-Gil JF. Inequalities in the association between adherence to the Mediterranean diet and physical fitness in the young population during the COVID-19 lockdown. Article. Nutr Hosp. Apr 20 2023;40(2):391–399. Desigualdades en la asociacion entre la adherencia a la dieta mediterranea y la condicion fisica en la poblacion joven durante el confinamiento de la COVID-19. doi:10.20960/nh.04225 36748428 | Study design; Outcome
142 | Brinkworth GD, Wycherley TP, Taylor PJ, Thompson CH. A Health Care Professional Delivered Low Carbohydrate Diet Program Reduces Body Weight, Haemoglobin A1c, Diabetes Medication Use and Cardiovascular Risk Markers-A Single-Arm Intervention Analysis. Article. Nutrients. Oct 20 2022;14(20)doi:10.3390/nu14204406 | Study design; Intervention or Exposure - Foods/Beverages Not Reported; Duration of Intervention
143 | Bromage S, Daria T, Lander RL, Diet and Nutrition Status of Mongolian Adults. Nutrients. May 22 2020;12(5)doi:10.3390/nu12051514 | Size or Power
144 | Bros-Konopielko M, Bialek A, Oleszczuk-Modzelewska L, Zaleskiewicz B, Rozanska-Waledziak A, Czajkowski K. Nutritional, Anthropometric and Sociodemographic Factors Affecting Fatty Acids Profile of Pregnant Women's Serum at Labour-Chemometric Studies. Nutrients. Aug 25 2021;13(9)doi:10.3390/nu13092948 | Intervention or Exposure; Outcome
145 | Brum SZ, Franchini B, Moura AP. Body Composition, Nutritional Intake Assessment, and Perceptions about Diet for Health and Performance: An Exploratory Study for Senior Futsal Players. Nutrients. Mar 16 2023;15(6)doi:10.3390/nu15061428 | Study design
146 | Bruno R, Petrella E, Bertarini V, Pedrielli G, Neri I, Facchinetti F. Adherence to a lifestyle programme in overweight/obese pregnant women and effect on gestational diabetes mellitus: a randomized controlled trial. Matern Child Nutr. Jul 2017;13(3)doi:10.1111/mcn.12333 | Outcome
147 | Buckingham-Schutt LM, Ellingson LD, Vazou S, Campbell CG. The Behavioral Wellness in Pregnancy study: a randomized controlled trial of a multi-component intervention to promote appropriate weight gain. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't; Research Support, U.S. Gov't, Non-P.H.S. Am J Clin Nutr. Apr 1 2019;109(4):1071–1079. doi: 10.1093/ajcn/nqy359 30949691 | Intervention or Exposure; Comparator
148 | Buckland G, Northstone K, Emmett PM, Taylor CM. The inflammatory potential of the diet in childhood is associated with cardiometabolic risk in adolescence/young adulthood in the ALSPAC birth cohort. Article. Eur J Nutr. Oct 2022;61(7):3471–3486. doi: 10.1007/s00394-022-02860-9 35596006 | Intervention or Exposure - Foods/Beverages Not Reported
149 | Bulung NH, Yildiz E. The Relationship between Biochemical and Hemoglobin Results and Quality Index Scores of the Mediterranean Diet of Pregnant Women in the First and the Third Trimester. Article. Progress in Nutrition. 2021;23(4)doi:10.23751/pn.v23i4.11333 | Intervention or Exposure; Outcome
150 | Burton ET, Smith WA. Mindful Eating and Active Living: Development and Implementation of a Multidisciplinary Pediatric Weight Management Intervention. Nutrients. May 14 2020;12(5)doi:10.3390/nu12051425 | Study design; Intervention or Exposure
151 | Cacau LT, Bensenor IM, Goulart AC, Adherence to the Planetary Health Diet Index and Obesity Indicators in the Brazilian Longitudinal Study of Adult Health (ELSA-Brasil). Article. Nutrients. Oct 20 2021; 13(11)doi: 10.3390/nu13113691 | Study design
152 | Cai L, Dai M, Lin L, Incidence of childhood overweight and obesity and its association with weight-related attitudes and behaviors in China: a national longitudinal study. Article. Int J Behav Nutr Phys Act. Nov 3 2018; 15(1): 108. doi: 10.1186/s12966-018-0737-6 30390717 | Intervention or Exposure; Publication date
153 | Cai Q, Dekker LH, Vinke PC, Diet quality and incident chronic kidney disease in the general population: The Lifelines Cohort Study. Article. Clin Nutr. Sep 2021;40(9):5099–5105. doi:10.1016/j.clnu.2021.07.033 34461583 | Outcome
154 | Cai R, Chao J, Li D, Zhang M, Kong L, Wang Y. Effect of community-based lifestyle interventions on weight loss and cardiometabolic risk factors in obese elderly in China: A randomized controlled trial. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Exp Gerontol. Dec 2019;128:110749. doi:10.1016/j.exger.2019.110749 31644921 | Intervention or Exposure - Foods/Beverages Not Reported
155 | Calleja M, Caetano Feitoza N, Falk B, Increased dairy product consumption as part of a diet and exercise weight management program improves body composition in adolescent females with overweight and obesity-A randomized controlled trial. Pediatr Obes. Dec 2020;15(12):e12690. doi: 10.1111/ijpo.12690 32602233 | Intervention or Exposure - Foods/Beverages Not Reported
156 | Callender C, Johnson B, Musaad S, Thompson D. Baseline Diet Quality Using the Healthy Eating Index-2015 for African American Girls in an Online Obesity Prevention Program. Journal of the Academy of Nutrition & Dietetics. 2022;122(10):A122–A122. | Publication status
157 | Calvo-Malvar M, Benitez-Estevez AJ, Sanchez-Castro J, Leis R, Gude F. Effects of a Community-Based Behavioral Intervention with a Traditional Atlantic Diet on Cardiometabolic Risk Markers: A Cluster Randomized Controlled Trial ("The GALIAT Study"). Nutrients. Apr 7 2021;13(4)doi:10.3390/nu13041211 | Outcome
158 | Campanella A, lacovazzi PA, Misciagna G, The Effect of Three Mediterranean Diets on Remnant Cholesterol and Non-Alcoholic Fatty Liver Disease: A Secondary Analysis. Journal Article; Randomized Controlled Trial. Nutrients. Jun 4 2020;12(6)doi:10.3390/nu12061674 | Outcome
159 | Cano-lbanez N, Bueno-Cavanillas A, Martinez-Gonzalez MA, Effect of changes in adherence to Mediterranean diet on nutrient density after 1-year of follow-up: results from the PREDIMED-Plus Study. Eur J Nutr. Sep 2020;59(6):2395–2409. doi: 10.1007/S00394-019-02087-1 31523780 | Outcome
160 | Cano-lbanez N, Martinez-Galiano JM, Luque-Fernandez MA, Martin-Pelaez S, Bueno-Cavanillas A, Delgado-Rodriguez M. Maternal Dietary Patterns during Pregnancy and Their Association with Gestational Weight Gain and Nutrient Adequacy. Int J Environ Res Public Health. Oct 28 2020;17(21)doi:10.3390/ijerph17217908 | Study design
161 | Cano-lbanez N, Quintana-Navarro GM, Alcala-Diaz JF, Long-term effect of a dietary intervention with two-healthy dietary approaches on food intake and nutrient density in coronary patients: results from the CORDIOPREV trial. Eur J Nutr. Sep 2022;61(6):3019–3036. doi:10.1007/s00394-022-02854-7 35348875 | Health Status- 100% CVD
162 | Cano-lbanez N, Serra-Majem L, Martin-Pelaez S, Association between the Prime Diet Duality Score and depressive symptoms in a Mediterranean population with metabolic syndrome. Cross-sectional and 2-year follow-up assessment from PREDIMED-PLUS study. Article in Press. Br J Nutr. Sep 28 2022;128(6):1170–1179. doi:10.1017/S0007114521004323 34713791 | Outcome
163 | Cao YJ, Wang HJ, Zhang B, Associations of fat and carbohydrate intake with becoming overweight and obese: an 11-year longitudinal cohort study. Br J Nutr. Oct 14 2020;124(7):715–728. doi:10.1017/S0007114520001579 32378502 | Intervention or Exposure
164 | Carbert NS, Brussoni M, Geller J, Masse LC. Moderating effects of family environment on overweight/obese adolescents' dietary behaviours. Article. Appetite. Mar 1 2019;134:69–77. doi:10.1016/j.appet.2018.12.034 30590079 | Study design; Outcome
165 | Carbone F, Ciaula AD, Pagano S, Anti-ApoA-1 IgGs predict resistance to waist circumference reduction after Mediterranean diet. Eur J Clin Invest. Mar 2021;51(3):e13410. doi:10.1111/eci.13410 32918294 | Intervention or Exposure; Comparator
166 | Cardenas-Fuentes G, Lassale C, Martinez-Gonzalez MA, Anthropometric Variables as Mediators of the Association of Changes in Diet and Physical Activity With Inflammatory Profile. J Gerontol A Biol Sci Med Sci. Oct 13 2021;76(11):2021–2029. doi: 10.1093/gerona/glab072 33693782 | Outcome; Comparator
167 | Carter S, Parsons C, Ward K, Clynes M, Dennison EM, Cooper C. Body mass index, prudent diet score and social class across three generations: evidence from the Hertfordshire Intergenerational Study. BMJ Nutr Prev Health. 2021;4(1):36–41. doi: 10.1136/bmjnph-2020-000178 | Intervention or Exposure; Comparator
168 | Casas R, Castro-Barquero S, Crovetto F, Maternal Dietary Inflammatory Index during Pregnancy Is Associated with Perinatal Outcomes: Results from the IMPACT BCN Trial. Article. Nutrients. May 29 2022;14(11)doi:10.3390/nu14112284 | Intervention or Exposure; Outcome
169 | Casas R. Moving towards a Healthier Dietary Pattern Free of Ultra-Processed Foods. Article. Nutrients. Dec 28 2021;14(1)doi:10.3390/nu14010118 | Study design; Publication status
170 | Casperson SL, Jahns L, Duke SE, Incorporating the Dietary Guidelines for Americans Vegetable Recommendations into the Diet Alters Dietary Intake Patterns of Other Foods and Improves Diet Quality in Adults with Overweight and Obesity. J Acad Nutr Diet. Jul 2022; 122(7): 1345–1354 e1. doi:10.1016/j.jand.2022.03.008 35278698 | Duration of Intervention; Comparator
171 | Castellana F, Zupo R, Bortone I, Traditional Old Dietary Pattern of Castellana Grotte (Apulia) Is Associated with Healthy Outcomes. Nutrients. Oct 12 2020;12(10)doi:10.3390/nu12103097 | Size or Power
172 | Castro EA, Carraca EV, Cupeiro R, The Effects of the Type of Exercise and Physical Activity on Eating Behavior and Body Composition in Overweight and Obese Subjects. Article. Nutrients. Feb 20 2020;12(2)doi:10.3390/nu12020557 | Intervention or Exposure
173 | Castro TG, Gerritsen S, Teixeira JA, An index measuring adherence to New Zealand Infant Feeding Guidelines has convergent validity with maternal socio-demographic and health behaviours and with children's body size. Br J Nutr. Apr 14 2022;127(7):1073–1085. doi:10.1017/S0007114521001720 34212833 | Intervention or Exposure - Foods/Beverages Not Reported
174 | Castro-Barquero S, Casas R, Rimm EB, Loss of Visceral Fat is Associated with a Reduction in Inflammatory Status in Patients with Metabolic Syndrome. Mol Nutr Food Res. Feb 2023;67(4):e2200264. doi:10.1002/mnfr.202200264 36416291 | Intervention or Exposure; Comparator
175 | Castro-Barquero S, Ribo-Coll M, Lassale C, Mediterranean Diet Decreases the Initiation of Use of Vitamin K Epoxide Reductase Inhibitors and Their Associated Cardiovascular Risk: A Randomized Controlled Trial. Article. Nutrients. Dec 19 2020;12(12):1–14. doi:10.3390/nu12123895 | Intervention or Exposure; Outcome
176 | Cea-Soriano L, Pulido J, Franch-Nadal J, Mediterranean diet and diabetes risk in a cohort study of individuals with prediabetes: propensity score analyses. Article in Press. Diabet Med. Jun 2022;39(6):e14768. doi: 10.1111/dme.14768 34897805 | Outcome
177 | Chairistanidou C, Karatzi K, Karaglani E, Diet quality in association to lipidaemic profile in adults of families at high-risk for type 2 diabetes in Europe: The Feel4Diabetes study. Nutr Metab Cardiovasc Dis. May 2022;32(5):1175–1185. doi:10.1016/j.numecd.2022.01.036 35277326 | Outcome
178 | Chaltiel D, Julia C, Adjibade M, Touvier M, Hercberg S, Kesse-Guyot E. Adherence to the new French dietary guidelines and risk of overweight and obesity. Proceedings of the Nutrition Society. 2020;79(OCE2):E232–E232. doi: 10.1017/s0029665120001809 | Publication status
179 | Champagne C, Miketinas D, Sacks F, Bray G. Weight loss, adherence, and dietary intakes of free-living adults consuming calorie-restricted diets varying in macronutrient composition: the POUNDS LOST Study. Journal: Conference Abstract. Proceedings of the Nutrition Society. 2020;79(OCE2):E310–E310. doi:10.1017/s002966512000258x | Publication status
180 | Chang AR, Gummo L, Yule C, Effects of a Dietitian-Led, Telehealth Lifestyle Intervention on Blood Pressure: Results of a Randomized, Controlled Trial. J Am Heart Assoc. Oct 4 2022; 11(19):e027213. doi: 10.1161/JAHA.122.027213 36172955 | Intervention or Exposure
181 | Chang SL, Lee KJ, Nfor ON, Vegetarian Diets along with Regular Exercise: Impact on High-Density Lipoprotein Cholesterol Levels among Taiwanese Adults. Medicina (Kaunas). Feb 13 2020;56(2)doi:10.3390/medicina56020074 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
182 | Charkamyani F, Khedmat L, Hosseinkhani A. Decreasing the main maternal and fetal complications in women undergoing in vitro fertilization (IVF) trained by nutrition and healthy eating practices during pregnancy. J Matern Fetal Neonatal Med. Jun 2021;34(12):1855–1867. doi:10.1080/14767058.2019.1651267 31429355 | Health Status
183 | Chaumont S, Quinquis L, Monnerie B, A poor diet quality is associated with more gas-related symptoms and a decreased quality of life in French adults. Article. Br J Nutr. May 23 2022;129(4):1–27. doi:10.1017/S0007114522001593 | Outcome
184 | Chebet JJ, Thomson CA, Kohler LN, Association of Diet Quality and Physical Activity on Obesity-Related Cancer Risk and Mortality in Black Women: Results from the Women's Health Initiative. Cancer Epidemiol Biomarkers Prev. Mar 2020;29(3):591–598. doi: 10.1158/1055-9965.EPI-19-1063 31915146 | Outcome
185 | Chen B, Zeng J, Qin M, The Association Between Plant-Based Diet Indices and Obesity and Metabolic Diseases in Chinese Adults: Longitudinal Analyses From the China Health and Nutrition Survey. Front Nutr. 2022;9:881901. doi:10.3389/fnut.2022.881901 35795587 | Country
186 | Chen GC, Arthur R, Mossavar-Rahmani Y, Adherence to Recommended Eating Patterns Is Associated With Lower Risk of Peripheral Arterial Disease: Results From the Women's Health Initiative. Article. Hypertension. Aug 2021;78(2):447–455. doi: 10.1161/HYPERTENSIONAHA.121.17432 34176290 | Outcome
187 | Chen LW, Aubert AM, Shivappa N, Associations of maternal dietary inflammatory potential and quality with offspring birth outcomes: An individual participant data pooled analysis of 7 European cohorts in the ALPHABET consortium. PLoS Med. Jan 2021;18(1):e1003491. doi:10.1371/journal.pmed.1003491 33476335 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
188 | Chen M, Xu Y, Wang X, Shan S, Cheng G. Association between the prudent dietary pattern and blood pressure in Chinese adults is partially mediated by body composition. Front Nutr. Mar 23 2023; 10:1131126. doi:10.3389/fnut.2023.1131126 37032775 | Study design
189 | Chen P, Yang Z, Fan Z, Associations of adherence to Mediterranean-like diet pattern with incident rosacea: A prospective cohort study of government employees in China. Front Nutr. 2023;10:1092781. doi:10.3389/fnut.2023.1092781 36819686 | Outcome
190 | Chen Q, Wu W, Yang H, A Vegetable Dietary Pattern Is Associated with Lowered Risk of Gestational Diabetes Mellitus in Chinese Women. Article. Diabetes Metab J. Dec 2020;44(6):887–896. doi:10.4093/dmj.2019.0138 33081427 | Intervention or Exposure; Outcome
191 | Chen Y, Kang M, Kim H, Xu W, Lee JE. Associations of dietary patterns with obesity and weight change for adults aged 18–65 years: Evidence from the China Health and Nutrition Survey (CHNS). PLoS One. 2023;18(1):e0279625. doi: 10.1371/journal.pone.0279625 36696382 | Country
192 | Chen Y, Qin Y, Zhang Z, Association of the low-carbohydrate dietary pattern with postpartum weight retention in women. Food Funct. Nov 1 2021;12(21):10764–10772. doi:10.1039/d1fo00935d 34609398 | Study design
193 | Chen Y, Zhou T, Sun D, Distinct genetic subtypes of adiposity and glycemic changes in response to weight-loss diet intervention: the POUNDS Lost trial. Article. Eur J Nutr. Feb 2021;60(1):249–258. doi:10.1007/s00394-020-02244-x 32274554 | Intervention or Exposure
194 | Chen Z, Drouin-Chartier JP, Li Y, Changes in Plant-Based Diet Indices and Subsequent Risk of Type 2 Diabetes in Women and Men: Three U.S. Prospective Cohorts. Diabetes Care. Mar 2021;44(3):663–671. doi:10.2337/dc20-1636 33441419 | Study design; Outcome
195 | Chen Z, Qian F, Liu G, Prepregnancy plant-based diets and the risk of gestational diabetes mellitus: a prospective cohort study of 14,926 women. Am J Clin Nutr. Dec 1 2021;114(6):1997–2005. doi:10.1093/ajcn/nqab275 34510175 | Outcome
196 | Cheng J, Costacou T, Rockette-Wagner B, Perceived and calculated diet quality improvements in a randomized mHealth weight loss trial. Article in Press. Behav Med. Apr-Jun 2024;50(2):164–169. doi: 10.1080/08964289.2023.2178374 36789848 | Outcome
197 | Chiu THT, Chang CC, Lin CL, Lin MN. A Vegetarian Diet Is Associated with a Lower Risk of Cataract, Particularly Among Individuals with Overweight: A Prospective Study. Article. J Acad Nutr Diet. Apr 2021;121(4):669–677 e1. doi: 10.1016/j.jand.2020.11.003 33309591 | Outcome
198 | Chiu THT, Chang HR, Wang LY, Chang CC, Lin MN, Lin CL. Vegetarian diet and incidence of total, ischemic, and hemorrhagic stroke in 2 cohorts in Taiwan. Neurology. Mar 17 2020;94(11):e1112–e1121. doi:10.1212/WNL.0000000000009093 32102976 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome; Country
199 | Chlebowski RT, Aragaki AK, Anderson GL, Low-fat dietary pattern and long-term breast cancer incidence and mortality: The Women’s Health Initiative randomized clinical trial. Journal: Conference Abstract. Journal of Clinical Oncology. May 20 2019;37(15_suppl):520–520. doi:10.1200/JCQ.2019.37.15_suppl.520 | Outcome
200 | Chmurzynska A, Mlodzik-Czyzewska MA, Galinski G, Polymorphism of CD36 Determines Fat Discrimination but Not Intake of High-Fat Food in 20- to 40-Year-Old Adults. Article. J Nutr. Aug 1 2020;150(8):2016–2022. doi:10.1093/jn/nxaa136 32455431 | Intervention or Exposure
201 | Chmurzynska A, Muzsik A, Krzyzanowska-Jankowska P, Madry E, Walkowiak J, Bajerska J. PPARG and FTO polymorphism can modulate the outcomes of a central European diet and a Mediterranean diet in centrally obese postmenopausal women. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Nutr Res. Sep 2019;69:94–100. doi:10.1016/j.nutres.2019.08.005 31675538 | Intervention or Exposure - Foods/Beverages Not Reported
202 | Choi YJ, Crimmins EM, Ailshire JA. Food insecurity, food environments, and disparities in diet quality and obesity in a nationally representative sample of community-dwelling older Americans. Article. Prev Med Rep. Oct 2022;29:101912. doi:10.1016/j.pmedr.2022.101912 35911578 | Study design
203 | Christensen RAG, High S, Wharton S, Sequential diets and weight loss: Including a low-carbohydrate high-fat diet with and without time-restricted feeding. Nutrition. Nov-Dec 2021;91–92:111393. doi: 10.1016/j.nut.2021.111393 | Intervention or Exposure - Foods/Beverages Not Reported
204 | Chwyl C, Wright N, G MT-M, M LB, E MF. Remotely Delivered Behavioral Weight Loss Intervention Using an Ad Libitum Plant-Based Diet: Pilot Acceptability, Feasibility, and Preliminary Results. JMIR Form Res. Jun 23 2022;6(6):e37414. doi:10.2196/37414 35737443 | Study design; Intervention or Exposure
205 | Cincione IR, Graziadio C, Marino F, Short-time effects of ketogenic diet or modestly hypocaloric Mediterranean diet on overweight and obese women with polycystic ovary syndrome. J Endocrinol Invest. Apr 2023;46(4):769–777. doi:10.1007/s40618-022-01943-y 36401759 | Health Status; Duration of Intervention
206 | Cipryan L, Dostal T, Litschmannova M, Hofmann P, Maffetone PB, Laursen PB. Effects of a Very Low-Carbohydrate High-Fat Diet and High-Intensity Interval Training on Visceral Fat Deposition and Cardiorespiratory Fitness in Overfat Individuals: A Randomized Controlled Clinical Trial. Front Nutr. Dec 21 2021;8:785694. doi: 10.3389/fnut.2021.785694 34993222 | Intervention or Exposure - Foods/Beverages Not Reported
207 | Cipryan L, Dostal T, Plews DJ, Hofmann P, Laursen PB. Adiponectin/leptin ratio increases after a 12-week very low-carbohydrate, high-fat diet, and exercise training in healthy individuals: A non-randomized, parallel design study. Nutr Res. Mar 2021;87:22–30. doi:10.1016/j.nutres.2020.12.012 33596508 | Intervention or Exposure - Foods/Beverages Not Reported
208 | Clark JS, Dyer KA, Davis CR, Adherence to a Mediterranean Diet for 6 Months Improves the Dietary Inflammatory Index in a Western Population: Results from the MedLey Study. Nutrients. Jan 11 2023;15(2)doi:10.3390/nu15020366 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
209 | Cloetens L, Sedin A, Landin-Olsson M. Can a Nordic diet be implemented as a new strategy for successful long-term weight loss maintenance in subjects with obesity? Journal: Conference Abstract. Proceedings of the Nutrition Society. 2020;79(OCE2):E87–E87. doi: 10.1017/s002966512000035x | Publication status
210 | Coates AM, Morgillo S, Yandell C, Effect of a 12-Week Almond-Enriched Diet on Biomarkers of Cognitive Performance, Mood, and Cardiometabolic Health in Older Overweight Adults. Journal Article; Randomized Controlled Trial. Nutrients. Apr 23 2020; 12(4)doi: 10.3390/nu12041180 | Intervention or Exposure; Comparator
211 | Cobos-Palacios L, Munoz-Ubeda M, Ruiz-Moreno Ml, Lifestyle Modification Program on a Metabolically Healthy Elderly Population with Overweight/Obesity, Young-Old vs. Old-Old. CONSEQUENCES of COVID-19 Lockdown in This Program. Article. Int J Environ Res Public Health. Nov 13 2021; 18(22)doi: 10.3390/ijerph182211926 | Study design; Intervention or Exposure; Comparator
212 | Cobos-Palacios L, Ruiz-Moreno Ml, Vilches-Perez A, Metabolically healthy obesity: Inflammatory biomarkers and adipokines in elderly population. PLoS One. 2022;17(6):e0265362. doi: 10.1371/journal.pone.0265362 35679338 | Study design
213 | Coelho DB, Lopes LMP, de Oliveira EC, Baseline Diet Quality Is Related to Changes in the Body Composition and Inflammatory Markers: An Intervention Study Based on Resistance Training and Nutritional Advice. Biomed Res Int. Nov 25 2021;2021:6681823. doi:10.1155/2021/6681823 34869768 | Size or Power
214 | Cohen CC, Perng W, Sauder KA, Maternal Diet Quality During Pregnancy and Offspring Hepatic Fat in Early Childhood: The Healthy Start Study. J Nutr. Apr 2023;153(4):1122–1132. doi: 10.1016/j.tjnut.2023.01.039 36796482 | Outcome
215 | Collins T, Geana M, Overton K, Use of a Smartphone App Versus Motivational Interviewing to Increase Walking Distance and Weight Loss in Overweight/Obese Adults With Peripheral Artery Disease: Pilot Randomized Trial. JMIR Form Res. Feb 3 2022;6(2):e30295. doi: 10.2196/30295 35113020 | Health Status- 100% CVD; Comparator
216 | Comas Rovira M, Moreno Baro A, Burgaya Guiu N, The influence of obesity and diet quality on fetal growth and perinatal outcome. Nutr Hosp. Dec 20 2022;39(6):1205–1211. Influencia de la obesidad y la calidad de la dieta en el crecimiento fetal y resultados perinatales. doi:10.20960/nh.04076 36134591 | Outcome
217 | Condorelli RA, Aversa A, Basile L, Beneficial Effects of the Very-Low-Calorie Ketogenic Diet on the Symptoms of Male Accessory Gland Inflammation. Nutrients. Mar 4 2022;14(5)doi:10.3390/nu14051081 | Intervention or Exposure; Comparator
218 | Conradie C, Baumgartner J, Malan L, A Priori and a Posteriori Dietary Patterns among Pregnant Women in Johannesburg, South Africa: The NuPED Study. Article. Nutrients. Feb 9 2021;13(2):1–23. doi:10.3390/nu13020565 | Outcome
219 | Constant A, Boulic G, Lommez A, Chaillou R, Guy-Grand B, Raffin S. Locally implemented prevention programs may reverse weight trajectories in half of children with overweight/obesity amid low child-staff ratios: results from a quasi-experimental study in France. BMC Public Health. Jun 15 2020;20(1):941. doi:10.1186/s12889-020-09080-y 32539822 | Intervention or Exposure
220 | Corsi S, lodice S, Shannon O, Mitochondrial DNA methylation is associated with Mediterranean diet adherence in a population of older adults with overweight and obesity. Proceedings of the Nutrition Society. 2020;79(OCE2):E95–E95. doi: 10.1017/S0029665120000439 | Publication status
221 | Costa S, Pinto A, Santos AC, Oliveira A. The association of problematic eating behaviours with food quality and body mass index at 7 years of age. Article. Eur J Clin Nutr. Apr 2019;73(4):549–557. doi:10.1038/s41430-018-0169-z 29748660 | Study design
222 | Costanza J, Camanni M, Ferrari MM, Assessment of pregnancy dietary intake and association with maternal and neonatal outcomes. Pediatr Res. Jun 2022;91(7):1890–1896. doi:10.1038/s41390-021-01665-6 34344991 | Intervention or Exposure
223 | Costello E, Goodrich J, Patterson WB, Diet Quality Is Associated with Glucose Regulation in a Cohort of Young Adults. Nutrients. Sep 10 2022;14(18)doi:10.3390/nu14183734 | Comparator
224 | Courten BD, Karim MN, Hodge A. 715-P: Diet Scores Associated with Increases in General and Abdominal Obesity in the Melbourne Collaborative Cohort. Diabetes. 2020;69:N.PAG–N.PAG. | Publication status
225 | Covington L, Armstrong B, Trude ACB, Black MM. Longitudinal Associations Among Diet Quality, Physical Activity and Sleep Onset Consistency With Body Mass Index z-Score Among Toddlers in Low-income Families. Ann Behav Med. Jun 28 2021;55(7):653–664. doi: 10.1093/abm/kaaa100 33196078 | Intervention or Exposure
226 | Cozzi GD, Blanchard CT, Champion ML, Factors Associated with Appropriate Gestational Weight Gain among Women with Obesity. Am J Perinatol. Feb 2022;39(3):272–280. doi:10.1055/s-0040-1715529 32854132 | Intervention or Exposure
227 | Crimarco A, Fielding-Singh P, Landry M, Gardner CD. Abstract P126: Identifying Successful Predictors Of Body Fat Reduction In The Dietfits Trial. Journal: Conference Abstract. Circulation. May 25 2021;143(Suppl_1)doi:10.1161/circ.143.suppl_1.P126 | Intervention or Exposure; Publication status
228 | Croll PH, Voortman T, Vernooij MW, The association between obesity, diet quality and hearing loss in older adults. Article. Aging (Albany NY). Jan 4 2019;11(1):48–62. doi:10.18632/aging.101717 30609412 | Outcome
229 | Crovetto F, Crispi F, Casas R, Effects of Mediterranean Diet or Mindfulness-Based Stress Reduction on Prevention of Small-for-Gestational Age Birth Weights in Newborns Born to At-Risk Pregnant Individuals: The IMPACT BCN Randomized Clinical Trial. JAMA. Dec 7 2021;326(21):2150–2160. doi:10.1001/jama.2021.20178 34874420 | Outcome; Comparator
230 | Crovetto M, Sepulveda MJ. Relationship between dietary energy intake, nutritional status and cardiovascular risk in adults from the communes of Quellon and Chonchi, Chiloe, Chile. J Prev Med Hyg. 2022;63(3):E435–E441. doi: 10.15167/2421-4248/jpmh2022.63.3.2486 36415288 | Study design; Intervention or Exposure
231 | Cuevas-Sierra A, Milagro FI, Guruceaga E, . A weight-loss model based on baseline microbiota and genetic scores for selection of dietary treatments in overweight and obese population. Article in Press. Clin Nutr. Aug 2022;41(8):>1712–1723. doi: 10.1016/j.clnu.2022.06.008 35777110 | Intervention or Exposure - Foods/Beverages Not Reported
232 | Cummings JR, Faith MS, Lipsky LM, Liu A, Mooney JT, Nansel TR. Prospective relations of maternal reward-related eating, pregnancy ultra-processed food intake and weight indicators, and feeding mode with infant appetitive traits. Int J Behav Nutr Phys Act. Aug 3 2022;19(1):100. doi:10.1186/s12966-022-01334-9 35922793 | Intervention or Exposure
233 | Cummins CB, Bowen-Jallow K, Tasnim S, One Size Does Not Fit All: Sociodemographic Factors Affecting Weight Loss in Adolescents. Article. Journal of Obesity. 2020;2020 | Intervention or Exposure
234 | Curci R, Bianco A, Franco I, The Effect of Low Glycemic Index Mediterranean Diet and Combined Exercise Program on Metabolic-Associated Fatty Liver Disease: A Joint Modeling Approach. J Clin Med. Jul 26 2022;11(15)doi:10.3390/jcm11154339 | Intervention or Exposure; Outcome; Comparator
235 | Cyr-Scully A, Howard AG, Sanzone E, Characterizing the urban diet: development of an urbanized diet index. Nutr J. Sep 9 2022;21(1):55. doi:10.1186/S12937-022-00807-8 36085037 | Study design
236 | Czekajto A, Rozanska D, Zatonska K, Szuba A, Regulska-llow B. Association between dietary patterns and metabolic syndrome in the selected population of Polish adults-results of the PURE Poland Study. Article. European journal of public health. 2019;29(2):335–340.30285088 | Study design
237 | Daily JW, Park S. Association of Plant-Based and High-Protein Diets with a Lower Obesity Risk Defined by Fat Mass in Middle-Aged and Elderly Persons with a High Genetic Risk of Obesity. Nutrients. Feb 20 2023;15(4)doi:10.3390/nu15041063 | Study design; Outcome
238 | Dakin M, Manneville F, Langlois J, Longitudinal patterns of lifestyle behaviours in adolescence: a latent transition analysis. Br J Nutr. Aug 28 2021; 126(4):621–631. doi: 10.1017/S0007114520004316 33143758 | Intervention or Exposure; Outcome; Comparator
239 | Dalrymple KV, Flynn AC, Seed PT, Associations between dietary patterns, eating behaviours, and body composition and adiposity in 3-year-old children of mothers with obesity. Pediatr Obes. May 2020;15(5):e12608. doi: 10.1111/ijpo.12608 31883218 | Study design
240 | Dalrymple KV, Flynn AC, Seed PT, Modifiable early life exposures associated with adiposity and obesity in 3-year old children born to mothers with obesity. Pediatr Obes. Nov 2021;16(11 ):e12801. doi: 10.1111/ijpo.12801 33998777 | Intervention or Exposure; Comparator
241 | Dalrymple KV, Vogel C, Flynn AC, Longitudinal dietary trajectories from pregnancy to 3 years post delivery in women with obesity: relationships with adiposity. Obesity (Silver Spring). Apr 2023;31(4):1159–1169. doi:10.1002/oby.23706 36876599 | Outcome
242 | Damsgaard CT, Papadaki A, Jensen SM, Higher protein diets consumed ad libitum improve cardiovascular risk markers in children of overweight parents from eight European countries. Article. J Nutr. Jun 2013; 143(6):810–7. doi: 10.3945/jn.112.173427 23596158 | Intervention or Exposure - Foods/Beverages Not Reported
243 | Daniel GD, Chen H, Bertoni AG, DASH diet adherence and cognitive function: Multi-ethnic study of atherosclerosis. Article. Clin NutrESPEN. Dec 2021;46:223–231. doi:10.1016/j.clnesp.2021.10.004 | Outcome
244 | Dardzinska JA, Malgorzewicz S, Szupryczynska N, Adherence to the 2021 dietary guidelines of the European Society of Cardiology on cardiovascular disease prevention in residents of the Pomeranian Voivodeship with increased cardiovascular risk. Pol Arch Intern Med. Jun 23 2023;133(6)doi:10.20452/pamw.16418 | Study design; Outcome
245 | Das SK, Bukhari AS, Taetzsch AG, Randomized trial of a novel lifestyle intervention compared with the Diabetes Prevention Program for weight loss in adult dependents of military service members. Article. Am J Clin Nutr. Oct 4 2021;114(4):1546–1559. doi: 10.1093/ajcn/nqab259 34375387 | Intervention or Exposure
246 | Davis B, Liu YH, Stampley J, The Association between Poor Diet Quality, Physical Fatigability and Physical Function in the Oldest-Old from the Geisinger Rural Aging Study. Geriatrics (Basel). Apr 15 2021;6(2)doi:10.3390/geriatrics6020041 | Outcome
247 | Davis BJK, Scrafford C, Bi X, Higgins KA, Barraj L, Murphy MM. Gestational Weight Gain, Diet Quality and Dairy Consumption: NHANES 2003–2012. Annals of Epidemiology. 2020;52:106–107. | Publication status
248 | Davis JA, Mohebbi M, Collier F, Diet quality and a traditional dietary pattern predict lean mass in Australian women: Longitudinal data from the Geelong Osteoporosis Study. Prev Med Rep. Mar 2021;21:101316. doi: 10.1016/j.pmedr.2021.101316 33505843 | Size or Power
249 | De Amicis R, Foppiani A, Galasso L, Weight Loss Management and Lifestyle Changes during COVID-19 Lockdown: A Matched Italian Cohort Study. Nutrients. Jul 14 2022;14(14)doi:10.3390/nu14142897 | Study design; Intervention or Exposure; Comparator
250 | de Arriba Munoz A, Garcia Castellanos MT, Cajal MD, Beisti Ortego A, Ruiz IM, Labarta Aizpun Jl. Automated growth monitoring app (GROWIN): a mobile Health (mHealth) tool to improve the diagnosis and early management of growth and nutritional disorders in childhood. Article in Press. J Am Med Inform Assoc. Aug 16 2022;29(9):1508–1517. doi:10.1093/jamia/ocac108 35799406 | Intervention or Exposure
251 | de Bona Coradi F, Anele CR, Goldani MZ, da Silva CH, Bernardi JR. Maternal diet quality and associations with body composition and diet quality of preschool children: A longitudinal study. PLoS One. 2023;18(5):e0284575. doi:10.1371/journal.pone.0284575 37167269 | Intervention or Exposure
252 | de Castro MBT, Cunha DB, Araujo MC, High protein diet promotes body weight loss among Brazilian postpartum women. Article. Maternal and Child Nutrition. 2019; 15(3) | Intervention or Exposure - Foods/Beverages Not Reported
253 | De Giuseppe R, Bocchi M, Maffoni S, Mediterranean Diet and Lifestyle Habits during Pregnancy: Is There an Association with Small for Gestational Age Infants? An Italian Single Centre Experience. Article. Nutrients. Jun 5 2021;13(6)doi:10.3390/nu13061941 | Study design
254 | De Giuseppe R, Calcaterra V, Biino G, Unhealthy lifestyle and oxidative damage in childhood obesity. Eat Weight Disord. Apr 2020;25(2):481–486. doi:10.1007/s40519-018-0626-7 30554325 | Study design; Intervention or Exposure
255 | de Lira CRN, Akutsu R, Coelho LG, Zandonadi RP, Costa PRF. Dietary Patterns, Occupational Stressors and Body Composition of Hospital Workers: A Longitudinal Study Comparing before and during the COVID-19 Pandemic. Int J Environ Res Public Health. Jan 25 2023;20(3)doi: 10.3390/ijerph20032166 | Study design
256 | de Luis D, Izaola O, Primo D, Aller R. A Randomized Trial with Two Hypocaloric Diets with Different Lipid Profiles and Effects on Serum Omentin-1 Levels in Obese Subjects. Article. Dis Markers. 2022;2022:6777283. doi: 10.1155/2022/6777283 35295321 | Intervention or Exposure
257 | de Luis D, Izaola O, Primo D. APOA-5 Genetic Variant rs662799: Role in Lipid Changes and Insulin Resistance after a Mediterranean Diet in Caucasian Obese Subjects. Dis Markers. 2021;2021:1257145. doi: 10.1155/2021/1257145 34422134 | Study design; Comparator
258 | de Luis DA, Izaola O, Primo D, Aller R. A circadian rhythm-related MTNR1B genetic variant (rs10830963) modulate body weight change and insulin resistance after 9months of a high protein/low carbohydrate vs a standard hypocaloric diet. Article. Journal of Diabetes and its Complications. 2020;34(4) | Intervention or Exposure - Foods/Beverages Not Reported
259 | de Luis DA, Izaola O, Primo D, Aller R. Dietary-fat effect of the rs10830963 polymorphism in MTNR1B on insulin resistance in response to 3 months weight-loss diets. Endocrinol Diabetes Nutr (Engl Ed). Jan 2020;67(1):43–52. Efecto del polimorfismo rs10830963 MTNR1B y la composicion de grasa de la dieta en la resistencia a la insulina tras la perdida de peso durante 3 meses. doi:10.1016/j.endinu.2019.02.007 30981681 | Intervention or Exposure - Foods/Beverages Not Reported
260 | de Luis DA, Izaola O, Primo D, Aller R. Different effects of high-protein/low-carbohydrate versus standard hypocaloric diet on insulin resistance and lipid profile: Role of rs16147 variant of neuropeptide Y. Article. Diabetes Research and Clinical Practice. 2019;156 | Intervention or Exposure
261 | de Luis DA, Izaola O, Primo D, Role of rs1501299 variant in the adiponectin gene on total adiponectin levels, insulin resistance and weight loss after a Mediterranean hypocaloric diet. Article. Diabetes Research and Clinical Practice. 2019;148:262–267.29154912 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
262 | de Luis DA, Primo D, Izaola O, Aller R. Role of resistin (rs7139228) gene polymorphism with metabolic response after a hypocaloric mediterranean diet. Endocrinol Diabetes Nutr (Engl Ed). Feb 2023;70(2):88–97. doi:10.1016/j.endien.2022.10.004 36841628 | Intervention or Exposure; Comparator
263 | de Luis DA, Primo D, Izaola O, Role of the variant in adiponectin gene rs266729 on weight loss and cardiovascular risk factors after a hypocaloric diet with the Mediterranean pattern. Article. Nutrition. 2019;60:1–5.30508762 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
264 | de Luis DA, Primo D, Izaola O, Gomez E, Bachiller R. Serum Lipid and Adiponectin Improvements after a Mediterranean Dietary Pattern in Non-G-Allele Carriers of the Variant rs3774261. Lifestyle Genom. 2020;13(6):164–171. doi: 10.1159/000508819 33075772 | Study design
265 | De Matteis C, Crudele L, Battaglia S, Identification of a Novel Score for Adherence to the Mediterranean Diet That Is Inversely Associated with Visceral Adiposity and Cardiovascular Risk: The Chrono Med Diet Score (CMDS). Nutrients. Apr 15 2023; 15(8)doi: 10.3390/nu15081910 | Study design
266 | De Miguel-Etayo P, Moreno LA, Santabarbara J, Diet quality index as a predictor of treatment efficacy in overweight and obese adolescents: The EVASYON study. Article. Clinical Nutrition. 2019;38(2):782–790.29730135 | Study design
267 | de Paula Mancilha T, Massarani FA, Vieira F, Donangelo CM, Koury JC. Birth weight, skeletal maturity and dietary patterns are associated with body composition compartments differently in male and female physically active adolescents. Nutr Health. Dec 2023;29(4):665–672. doi:10.1177/02601060221096514 35491704 | Study design
268 | de Seymour JV, Beck KL, Conlon CA, An Investigation of the Relationship Between Dietary Patterns in Early Pregnancy and Maternal/Infant Health Outcomes in a Chinese Cohort. Front Nutr. 2022;9:775557. doi:10.3389/fnut.2022.775557 35529458 | Outcome
269 | Deierlein AL, Ghassabian A, Kahn LG, Dietary Quality and Sociodemographic and Health Behavior Characteristics Among Pregnant Women Participating in the New York University Children's Health and Environment Study. Front Nutr. 2021;8:639425. doi: 10.3389/fnut.2021.639425 33898496 | Outcome
270 | Delgado-Floody P, Alvarez C, Caamano-Navarrete F, Jerez-Mayorga D, Latorre-Roman P. Influence of Mediterranean diet adherence, physical activity patterns, and weight status on cardiovascular response to cardiorespiratory fitness test in Chilean school children. Nutrition. Mar 2020;71:110621. doi:10.1016/j.nut.2019.110621 31874334 | Study design
271 | Deris H, Tominac P, Vuckovic F, Effects of low-calorie and different weight-maintenance diets on IgG glycome composition. Front Immunol. 2022;13:995186. doi:10.3389/fimmu.2022.995186 36211377 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
272 | Detopoulou P, Dedes V, Pylarinou I, Syka D, Tzirogiannis K, Panoutsopoulos Gl. Dietary acid load is associated with waist circumference in university students with low adherence to the Mediterranean diet: The potential role of ultra-processed foods. Article. Clin Nutr ESPEN. Aug 2023;56:43–51. doi:10.1016/j.clnesp.2023.05.005 37344082 | Study design; Intervention or Exposure
273 | Detopoulou P, Syka D, Koumi K, Dedes V, Tzirogiannis K, Panoutsopoulos Gl. Clinical Application of the Food Compass Score: Positive Association to Mediterranean Diet Score, Health Star Rating System and an Early Eating Pattern in University Students. Diseases. Jul 7 2022;10(3)doi:10.3390/diseases10030043 35225862 | Study design
274 | Di Renzo L, Marchetti M, Rizzo G, Adherence to Mediterranean Diet and Its Association with Maternal and Newborn Outcomes. Int J Environ Res Public Health. Jul 12 2022;19(14)doi:10.3390/ijerph19148497 | Study design
275 | Di Rosa C, Lattanzi G, Spiezia C, Mediterranean Diet versus Very Low-Calorie Ketogenic Diet: Effects of Reaching 5% Body Weight Loss on Body Composition in Subjects with Overweight and with Obesity-A Cohort Study. Int J Environ Res Public Health. Oct 11 2022;19(20)doi:10.3390/ijerph192013040 | Intervention or Exposure - Foods/Beverages Not Reported
276 | Diaz-Lopez A, Diaz-Torres S, Martin-Lujan F, Basora J, Arija V. Prenatal adherence to the Mediterranean diet decreases the risk of having a small-for-gestational-age baby, ECLIPSES study. Sci Rep. Aug 13 2022;12(1):13794. doi:10.1038/s41598-022-17957-8 35963881 | Outcome
277 | Ding M, Strohmaier S, Schernhammer E, Grand-maternal lifestyle during pregnancy and body mass index in adolescence and young adulthood: an intergenerational cohort study. Sci Rep. Sep 2 2020;10(1):14432. doi:10.1038/s41598-020-71461-5 32879408 | Intervention or Exposure; Outcome
278 | Ding Y, Xu F, Zhong C, Association between Chinese Dietary Guidelines Compliance Index for Pregnant Women and Risks of Pregnancy Complications in the Tongji Maternal and Child Health Cohort. Nutrients. Mar 3 2021;13(3)doi:10.3390/nu13030829 | Outcome
279 | Dinu M, Colombini B, Pagliai G, Effects of a dietary intervention with Mediterranean and vegetarian diets on hormones that influence energy balance: results from the CARDIVEG study. Int J Food Sci Nutr. May 2020;71(3):362–369. doi: 10.1080/09637486.2019.1658723 31462113 | Intervention or Exposure - Foods/Beverages Not Reported
280 | Dinu M, Pagliai G, Cesari F, Effects of a 3-month dietary intervention with a lacto-ovo-vegetarian diet on vitamin B(12) levels in a group of omnivores: results from the CARDIVEG (Cardiovascular Prevention with Vegetarian Diet) study. Article. Br J Nutr. Apr 14 2019; 121 (7):756–762. doi: 10.1017/S0007114518003835 30585554 | Study design; Comparator
281 | Dinu M, Pagliai G, Colombini B, Dietary intervention with vegetarian and mediterranean diets for cardiovascular prevention: effects on hormones involved in the energy balance. Journal: Conference Abstract. Nutrition, metabolism and cardiovascular diseases. 2019;29(8):881-. | Publication status
282 | Dinu M, Pagliai G, Lotti S, Giangrandi I, Colombini B, Sofi F. Adherence to Mediterranean Diet Measured through Medi-Lite Score and Obesity: A Retrospective Study. Article. Nutrients. Jun 10 2021;13(6)doi:10.3390/nu13062007 | Study design
283 | Djousse L, Zhou G, McClelland RL, Egg consumption, overall diet quality, and risk of type 2 diabetes and coronary heart disease: A pooling project of US prospective cohorts. Article. Clinical Nutrition. 2021;40(5):2475–2482.33932789 | Intervention or Exposure; Outcome
284 | Dolatkhah N, Toopchizadeh V, Barmaki S, The effect of an anti-inflammatory in comparison with a low caloric diet on physical and mental health in overweight and obese women with knee osteoarthritis: a randomized clinical trial. Eur J Nutr. Mar 2023;62(2):659–672. doi:10.1007/s00394-022-03017-4 36183308 | Duration of Intervention
285 | Dolin CD, Gross RS, Deierlein AL, Predictors of Gestational Weight Gain in a Low-Income Hispanic Population: Sociodemographic Characteristics, Health Behaviors, and Psychosocial Stressors. Int J Environ Res Public Health. Jan 4 2020;17(1)doi:10.3390/ijerph17010352 | Intervention or Exposure
286 | Dong H, Sun H, Cai C, A low-carbohydrate dietary pattern characterised by high animal fat and protein during the first trimester is associated with an increased risk of gestational diabetes mellitus in Chinese women: a prospective cohort study. Br J Nutr. Dec 28 2021; 126(12): 1872–1880. doi:10.1017/S0007114521000611 33597060 | Intervention or Exposure - Foods/Beverages Not Reported
287 | Dorans KS, Bazzano LA, Qi L, Effects of a Low-Carbohydrate Dietary Intervention on Hemoglobin A1c: A Randomized Clinical Trial. JAMA Netw Open. Oct 3 2022;5(10):e2238645. doi:10.1001/jamanetworkopen.2022.38645 36287562 | Intervention or Exposure - Foods/Beverages Not Reported
288 | Dorling JL, Martin CK, Yu Q, Mediators of weight change in underserved patients with obesity: exploratory analyses from the Promoting Successful Weight Loss in Primary Care in Louisiana (PROPEL) cluster-randomized trial. Am J Clin Nutr. Oct 6 2022;116(4):1112–1122. doi:10.1093/ajcn/nqac179 35762659 | Intervention or Exposure
289 | Dostal T, Plews DJ, Hofmann P, Laursen PB, Cipryan L. Effects of a 12-Week Very-Low Carbohydrate High-Fat Diet on Maximal Aerobic Capacity, High-Intensity Intermittent Exercise, and Cardiac Autonomic Regulation: Non-randomized Parallel-Group Study. Article. Front Physiol. 2019;10(JUL):912. doi:10.3389/fphys.2019.00912 31379612 | Intervention or Exposure - Foods/Beverages Not Reported
290 | Drummen M, Adam TC, Macdonald IA, Associations of changes in reported and estimated protein and energy intake with changes in insulin resistance, glycated hemoglobin, and BMI during the PREVIEW lifestyle intervention study. Am J Clin Nutr. Nov 8 2021;114(5):1847–1858. doi: 10.1093/ajcn/nqab247 34375397 | Intervention or Exposure; Duration of Intervention
291 | Drummen M, Tischmann L, Gatta-Cherifi B, High Compared with Moderate Protein Intake Reduces Adaptive Thermogenesis and Induces a Negative Energy Balance during Long-term Weight-Loss Maintenance in Participants with Prediabetes in the Postobese State: A PREVIEW Study. Article. J Nutr. Mar 1 2020;150(3):458–463. doi:10.1093/jn/nxz281 31754687 | Intervention or Exposure; Duration of Intervention
292 | Du S, Kim H, Rebholz CM. Higher Ultra-Processed Food Consumption Is Associated with Increased Risk of Incident Coronary Artery Disease in the Atherosclerosis Risk in Communities Study. Article. J Nutr. Dec 3 2021;151(12):3746–3754. doi:10.1093/jn/nxab285 34494108 | Outcome
293 | Dubois L, Bedard B, Goulet D, Prud'homme D, Tremblay RE, Boivin M. Eating behaviors, dietary patterns and weight status in emerging adulthood and longitudinal associations with eating behaviors in early childhood. Int J Behav Nutr Phys Act. Nov 16 2022;19(1):139. doi:10.1186/s12966-022-01376-z 36384744 | Intervention or Exposure; Outcome
294 | Dudum R, Juraschek SP, Appel LJ. Dose-dependent effects of lifestyle interventions on blood lipid levels: Results from the PREMIER trial. Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, N.I.H., Extramural. Patient Educ Couns. Oct 2019;102(10):1882–1891. doi:10.1016/j.pec.2019.05.005 31153659 | Intervention or Exposure; Outcome
295 | Dugas C, Belanger M, Perron J, Is a healthy diet associated with lower anthropometric and glycemic alterations in predisposed children born from mothers with gestational diabetes mellitus? Article. Nutrients. 2019;11(3) | Study design
296 | Duggan C, Tapsoba JD, Shivappa N, Changes in Dietary Inflammatory Index Patterns with Weight Loss in Women: A Randomized Controlled Trial. Cancer Prev Res (Phila). Jan 2021; 14(1):85–94. doi:10.1158/1940-6207.CAPR-20-0181 32859616 | Intervention or Exposure - Foods/Beverages Not Reported
297 | Dusanov S, Svendsen M, Ruzzin J, Effect of fatty fish or nut consumption on concentrations of persistent organic pollutants in overweight or obese men and women: A randomized controlled clinical trial. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Nutr Metab Cardiovasc Dis. Mar 9 2020;30(3):448–458. doi:10.1016/j.numecd.2019.11.006 32008913 | Intervention or Exposure
298 | Easton JF, Roman Sicilia H, Stephens CR. Classification of diagnostic subcategories for obesity and diabetes based on eating patterns. Article. Nutr Diet. Feb 2019;76(1):104–109. doi:10.1111/1747-0080.12495 30398002 | Study design; Intervention or Exposure
299 | Ebbeling CB, Bielak L, Lakin PR, Energy Requirement Is Higher During Weight-Loss Maintenance in Adults Consuming a Low-Compared with High-Carbohydrate Diet. Article. J Nutr. Aug 1 2020;150(8):2009–2015. doi:10.1093/jn/nxaa150 32470981 | Intervention or Exposure - Foods/Beverages Not Reported
300 | Ebbeling CB, Knapp A, Johnson A, Effects of a low-carbohydrate diet on insulin-resistant dyslipoproteinemia-a randomized controlled feeding trial. Article in Press. Am J Clin Nutr. Jan 11 2022;115(1): 154–162. doi:10.1093/ajcn/nqab287 34582545 | Intervention or Exposure
301 | Edwards CG, Zickgraf HF, Masterson TD, Rigby A. Use of a brief, retrospective Comprehensive Feeding Practices Questionnaire in a bariatric-surgery seeking adult population. Article. Eat Behav. Aug 2022;46:101655. doi:10.1016/j.eatbeh.2022.101655 35933926 | Study design; Health Status- 100% Hospitalized/Surgical
302 | El Mehadji D, Nadji Z, Zemri K, The evolutionary profile of celiac disease via the compliance to the gluten-free diet in the western Algerian region. Article. Romanian Journal of Diabetes, Nutrition and Metabolic Diseases. 2022;29(1):67–73. doi: 10.46389/rjd-2022-1076 | Study design
303 | Elliott LJ, Keown-Stoneman CDG, Birken CS, Vegetarian Diet, Growth, and Nutrition in Early Childhood: A Longitudinal Cohort Study. Pediatrics. Jun 1 2022;149(6)doi:10.1542/peds.2021-052598 | Intervention or Exposure - Foods/Beverages Not Reported
304 | Embling R, Price M, Lee M, Jones A, Wilkinson L. Associations between dietary variety, portion size, and body weight: Prospective evidence from 35,449 UK Biobank participants. Appetite. 2022;179:N.PAG–N.PAG. | Publication status
305 | Emond JA, Longacre MR, Titus LJ, Fast food intake and excess weight gain over a 1-year period among preschool-age children. Pediatr Obes. Apr 2020;15(4):e12602. doi: 10.1111/ijpo.12602 32003947 | Intervention or Exposure
306 | Eneli I, Xu J, Tindall A, Using a Revised Protein-Sparing Modified Fast (rPSMF) for Children and Adolescents with Severe Obesity: A Pilot Study. Article. Int J Environ Res Public Health. Aug 23 2019;16(17)doi: 10.3390/ijerph16173061 | Intervention or Exposure
307 | Epel E, Laraia B, Coleman-Phox K, Effects of a Mindfulness-Based Intervention on Distress, Weight Gain, and Glucose Control for Pregnant Low-Income Women: A Quasi-Experimental Trial Using the ORBIT Model. Controlled Clinical Trial; Journal Article. Int J Behav Med. Oct 2019;26(5):461–473. doi:10.1007/s12529-019-09779-2 30993601 | Intervention or Exposure - Foods/Beverages Not Reported
308 | Erdem NZ, Bayraktaroglu E, Samanci RA, Gecgil-Demir E, Tarakci NG, Mert-Biberoglu F. The effect of intermittent fasting diets on body weight and composition. Article. Clin Nutr ESPEN. Oct 2022;51:207–214. doi:10.1016/j.clnesp.2022.08.030 36184206 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
309 | Erdem NZ, Ozelgun D, Taskin HE, Avsar FM. Comparison of a pre-bariatric surgery very low-calorie ketogenic diet and the Mediterranean diet effects on weight loss, metabolic parameters, and liver size reduction. Sci Rep. Nov 30 2022;12(1):20686. doi: 10.1038/S41598-022-24959-z 36450844 | Health Status- 100% Hospitalized/Surgical; Duration of Intervention
310 | Esfandiar Z, Hosseini-Esfahani F, Mirmiran P, Azizi F. Diet quality indices and the risk of type 2 diabetes in the Tehran Lipid and Glucose Study. BMJ Open Diabetes Res Care. Sep 2022;10(5)doi:10.1136/bmjdrc-2022-002818 | Outcome
311 | Esteves GP, Swinton P, Sale C, Gualano B, Roschel H, Dolan E. Use of factor analysis to model relationships between bone mass and physical, dietary, and metabolic factors in frail and pre-frail older adults. J Appl Physiol (1985). Jul 1 2023;135(1):146–153. doi: 10.1152/japplphysiol.00129.2023 37227185 | Study design
312 | Evans WE, Raynor HA, Howie W, Associations between lifestyle intervention-related changes in dietary targets and migraine headaches among women in the Women's Health and Migraine (WHAM) randomized controlled trial. Obes Sci Pract. Apr 2020;6(2):119–125. doi:10.1002/osp4.376 32313669 | Comparator; Size or Power
313 | Facchinetti F, Vijai V, Petrella E, Food glycemic index changes in overweight/obese pregnant women enrolled in a lifestyle program: a randomized controlled trial. Journal Article; Randomized Controlled Trial. Am J Obstet Gynecol MFM. Aug 2019;1(3):100030. doi: 10.1016/j.ajogmf.2019.100030 33345794 | Intervention or Exposure; Comparator
314 | Facchinetti F, Vijay V, Petrella E, 78: impact of glycemic-index(GI) reduction on birthweight in overweight/obese pregnant women enrolled in a lifestyle program. Journal: Conference Abstract. American journal of obstetrics and gynecology. 2019;220(1):S62-. | Publication status
315 | Fagnant HS, Armstrong NJ, Lutz LJ, Self-reported eating behaviors of military recruits are associated with body mass index at military accession and change during initial military training. Appetite. Nov 1 2019;142:104348. doi:10.1016/j.appet.2019.104348 31299192 | Intervention or Exposure; Outcome
316 | Fan M, Jin Y. The Effects of Weight Perception on Adolescents' Weight-Loss Intentions and Behaviors: Evidence from the Youth Risk Behavior Surveillance Survey. Article. Int J Environ Res Public Health. Nov 17 2015;12(11):14640–68. doi: 10.3390/ijerph121114640 26593930 | Study design; Intervention or Exposure
317 | Fanelli Kuczmarski M, Hossain S, Beydoun MA, Maldonando A, Evans MK, Zonderman AB. Association of DASH and Depressive Symptoms with BMI over Adulthood in Racially and Socioeconomically Diverse Adults Examined in the HANDLS Study. Nutrients. Dec 3 2019; 11 (12)doi: 10.3390/nu11122934 | Intervention or Exposure
318 | Fanelli Kuczmarski M, Stave Shupe E, Pohlig RT, Rawal R, Zonderman AB, Evans MK. A Longitudinal Assessment of Diet Quality and Risks Associated with Malnutrition in Socioeconomic and Racially Diverse Adults. Article. Nutrients. Sep 2 2019;11(9)doi:10.3390/nu11092046 | Intervention or Exposure - Foods/Beverages Not Reported
319 | Fangupo LJ, Haszard JJ, Taylor BJ, Gray AR, Lawrence JA, Taylor RW. Ultra-Processed Food Intake and Associations With Demographic Factors in Young New Zealand Children. Article. J Acad Nutr Diet. Feb 2021;121(2):305–313. doi:10.1016/j.jand.2020.08.088 33500114 | Outcome
320 | Fantino M, Bichard C, Mistretta F, Bellisle F. Daily consumption of pistachios over 12 weeks improves dietary profile without increasing body weight in healthy women: A randomized controlled intervention. Appetite. Jan 1 2020;144:104483. doi: 10.1016/j.appet.2019.104483 31604062 | Intervention or Exposure; Comparator
321 | Farhadnejad H, Mokhtari E, Teymoori F, Association of the insulinemic potential of diet and lifestyle with risk of diabetes incident in Tehranian adults: a population based cohort study. Nutr J. Apr 23 2021;20(1):39. doi: 10.1186/s12937-021-00697-2 33892738 | Outcome
322 | Farrell ET, Wirth MD, McLain AC, Associations between the Dietary Inflammatory Index and Sleep Metrics in the Energy Balance Study (EBS). Nutrients. Jan 13 2023;15(2)doi:10.3390/nu15020419 | Intervention or Exposure; Outcome
323 | Fazzino TL, Dorling JL, Apolzan JW, Martin CK. Meal composition during an ad libitum buffet meal and longitudinal predictions of weight and percent body fat change: The role of hyper-palatable, energy dense, and ultra-processed foods. Article. Appetite. Dec 1 2021; 167:105592. doi: 10.1016/j.appet.2021.105592 34245802 | Duration of Intervention
324 | Feng J, Huang Y, Wang H, Association between adherence to the Dietary Approaches to Stop Hypertension diet and serum uric acid. Sci Rep. Apr 18 2023; 13(1 ):6347. doi: 10.1038/s41598-023-31762-x 37072454 | Study design
325 | Fenton S, Burrows TL, Collins CE, Rayward AT, Murawski B, Duncan MJ. Efficacy of a Multi-Component m-Health Diet, Physical Activity, and Sleep Intervention on Dietary Intake in Adults with Overweight and Obesity: A Randomised Controlled Trial. Nutrients. Jul 19 2021;13(7)doi:10.3390/nu13072468 | Intervention or Exposure; Outcome
326 | Fernandez CA, Potts K, Bazzano LA. Effect of ideal protein versus low-fat diet for weight loss: A randomized controlled trial. Article in Press. Obes Sci Pract. Jun 2022;8(3):299–307. doi:10.1002/osp4.567 | Intervention or Exposure; Outcome
327 | Fernandez de la Puente M, Hernandez-Alonso P, Canudas S, Modulation of Telomere Length by Mediterranean Diet, Caloric Restriction, and Exercise: Results from PREDIMED-Plus Study. Antioxidants (Basel). Oct 12 2021;10(10)doi:10.3390/antiox10101596 | Intervention or Exposure - Foods/Beverages Not Reported
328 | Fernandez-Lazaro Cl, Toledo E, Salas-Salvado J, PREDIMED-Plus trial: One-year changes in the quality of dietary carbohydrate intake and concurrent changes in cardiovascular risk factors. Journal: Conference Abstract. Annals of Nutrition and Metabolism. 2019;75:20–21.32564018 | Publication status
329 | Fernandez-Ruiz VE, Sole-Agusti M, Armero-Barranco D, Cauli O. Weight Loss and Improvement of Metabolic Alterations in Overweight and Obese Children Through the l(2)AO(2) Family Program: A Randomized Controlled Clinical Trial. Biol Res Nurs. Jul 2021;23(3):488–503. doi:10.1177/1099800420987303 33517762 | Intervention or Exposure
330 | Ferrara P, Sandullo F, Di Ruscio F, The impact of lacto-ovo-/lacto-vegetarian and vegan diets during pregnancy on the birth anthropometric parameters of the newborn. Article. J Matern Fetal Neonatal Med. Dec 2020;33(23):3900–3906. doi: 10.1080/14767058.2019.1590330 30909771 | Outcome
331 | Ferrara P, Sandullo F, Vecchio M, Length-weight growth analysis up to 12 months of age in three groups according to the dietary pattern followed from pregnant mothers and children during the first year of life. Minerva Pediatr (Torino). Apr 16 2021;doi:10.23736/S2724-5276.21.06262-5 | Intervention or Exposure; Outcome
332 | Ferreira ALL, Freitas-Costa N, da Silva Rosa Freire S, Association of pre-pregnancy maternal overweight/obesity and dietary intake during pregnancy with the concentrations of persistent organic pollutants in the human milk of women from Rio de Janeiro, Brazil. Environ Sci Pollut Res Int. Mar 2023;30(15):44999–45014. doi: 10.1007/s11356-023-25308-x 36701066 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
333 | Ferreira LB, Lobo CV, do Carmo AS, Souza R, Dos Santos LC. Dietary Patterns During Pregnancy and Their Association with Gestational Weight Gain and Anthropometric Measurements at Birth. Matern Child Health J. Jul 2022;26(7):1464–1472. doi: 10.1007/s10995-022-03392-8 35195821 | Study design
334 | Figueroa R, Saltzman JA, Kang A, Mini FN, Davison KK, Taveras EM. Antenatal dietary concordance among mothers and fathers and gestational weight gain: a longitudinal study. BMC Public Health. Jul 6 2020;20(1):1071. doi: 10.1186/s12889-020-09182-7 32631291 | Intervention or Exposure
335 | Fitzgerald MP, Hennigan K, O'Gorman CS, McCarron L. Obesity, diet and lifestyle in 9-year-old children with parentally reported chronic diseases: findings from the Growing Up in Ireland longitudinal child cohort study. Article. Ir J Med Sci. Feb 2019;188(1):29–34. doi:10.1007/s11845-018-1814-1 29728820 | Study design; Intervention or Exposure
336 | Fitzgibbon ML, Tussing-Humphreys L, Schiffer L, Fit and Strong! Plus: Twelve and eighteen month follow-up results for a comparative effectiveness trial among overweight/obese older adults with osteoarthritis. Prev Med. Dec 2020;141:106267. doi: 10.1016/j.ypmed.2020.106267 33022324 | Intervention or Exposure; Comparator
337 | Flor-Alemany M, Migueles JH, Acosta-Manzano P, Marin-Jimenez N, Baena-Garcia L, Aparicio VA. Assessing the Mediterranean diet adherence during pregnancy: Practical considerations based on the associations with cardiometabolic risk. Pregnancy Hypertens. Mar 2023;31:17–24. doi:10.1016/j.preghy.2022.11.007 36446188 | Outcome
338 | Flores AC, Heron C, Kim Jl, Prospective Study of Plant-Based Dietary Patterns and Diabetes in Puerto Rican Adults. J Nutr. Dec 3 2021; 151 (12):3795–3800. doi:10.1093/jn/nxab301 34515303 | Outcome
339 | Flores ME, Rivera-Pasquel M, Macias N, Dietary patterns in Mexican preschool children are associated with stunting and overweight. Article in Press. Rev Saude Publica. 2021;55:53. doi: 10.11606/s1518-8787.2021055002350 34406279 | Study design
340 | Flynn AC, Thompson JMD, Dalrymple KV, Childhood dietary patterns and body composition at age 6 years: the Children of SCOPE study. BrJ Nutr. Feb 26 2020;124(2):1–21. doi:10.1017/S0007114520000628 | Study design
341 | Forman EM, Manasse SM, Butryn ML, Crosby RD, Dallal DH, Crochiere RJ. Long-Term Follow-up of the Mind Your Health Project: Acceptance-Based versus Standard Behavioral Treatment for Obesity. Article. Obesity (Silver Spring). Apr 2019;27(4):565–571. doi:10.1002/oby.22412 30806492 | Intervention or Exposure
342 | Fossee E, Zamora AN, Peterson KE, Prenatal dietary patterns in relation to adolescent offspring adiposity and adipokines in a Mexico City cohort. J Dev Orig Health Dis. Jun 2023;14(3):371–380. doi:10.1017/S2040174422000678 36655507 | Outcome
343 | Fragiadakis GK, Wastyk HC, Robinson JL, Sonnenburg ED, Sonnenburg JL, Gardner CD. Long-term dietary intervention reveals resilience of the gut microbiota despite changes in diet and weight. Am J Clin Nutr. Jun 1 2020; 111(6):1127–1136. doi: 10.1093/ajcn/nqaa046 32186326 | Intervention or Exposure
344 | Francisco SC, Araujo LF, Griep RH, Adherence to the Dietary Approaches to Stop Hypertension (DASH) and hypertension risk: results of the Longitudinal Study of Adult Health (ELSA-Brasil). Br J Nutr. May 14 2020;123(9):1068–1077. doi:10.1017/S0007114520000124 31959262 | Did not account for at least 1 key confounder
345 | Franco AD, Morfino P, Aimo A. Plasma acylcarnitine, risk for heart failure or atrial fibrillation, and effects of the Mediterranean diet or obesity. Rev Esp Cardiol (Engl Ed). Aug 2022;75(8):621–622. doi:10.1016/j.rec.2022.01.008 35248520 | Publication status
346 | Franco I, Bianco A, Mirizzi A, Physical Activity and Low Glycemic Index Mediterranean Diet: Main and Modification Effects on NAFLD Score. Results from a Randomized Clinical Trial. Clinical Trial; Journal Article; Pragmatic Clinical Trial. Nutrients. Dec 28 2020;13(1)doi:10.3390/nu13010066 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
347 | Franklin KA, Lindberg E, Svensson J, Effects of a palaeolithic diet on obstructive sleep apnoea occurring in females who are overweight after menopause-a randomised controlled trial. Int J Obes (Lond). Oct 2022;46(10): 1833–1839. doi: 10.1038/s41366-022-01182-4 35879528 | Intervention or Exposure - Foods/Beverages Not Reported
348 | Fraschetti EC, Skelly LE, Ahmed M, Biancaniello EC, Klentrou P, Josse AR. The Influence of Increased Dairy Product Consumption, as Part of a Lifestyle Modification Intervention, on Diet Quality and Eating Patterns in Female Adolescents with Overweight/Obesity. Children (Basel). Nov 6 2022;9(11)doi:10.3390/children9111703 | Outcome; Comparator
349 | Fukuda Y, Yamamoto S, Kameda M. Association Between Lifestyle Characteristics and Body Mass Index of Mothers of Children With Allergic Diseases. J Clin Med Res. Dec 2019;11(12):780–788. doi:10.14740/jocmr3976 31803322 | Study design
350 | Fulkerson JA, Horning M, Barr-Anderson DJ, Weight outcomes of NU-HOME: a randomized controlled trial to prevent obesity among rural children. Article. Int J Behav Nutr Phys Act. Mar 19 2022;19(1):29. doi: 10.1186/s12966-022-01260-w 35305674 | Intervention or Exposure
351 | Gabiola J, Morales D, Quizon O, The EffectiveNess of Lifestyle with Diet and Physical Activity Education ProGram Among Prehypertensives and Stage 1 HyperTENsives in an Urban Community Setting (ENLIGHTEN) Study. J Community Health. Jun 2020;45(3):478–487. doi:10.1007/s10900-019-00764-0 31677046 | Intervention or Exposure; Country
352 | Gadgil MD, Ingram KH, Appiah D, Prepregnancy Protein Source and BCAA Intake Are Associated with Gestational Diabetes Mellitus in the CARDIA Study. Int J Environ Res Public Health. Oct 29 2022; 19(21 )doi: 10.3390/ijerph192114142 | Outcome
353 | Gadowski AM, Nanayakkara N, Heritier S, Association between dietary intake and lipid-lowering therapy: Prospective analysis of data from australian diabetes, obesity, and lifestyle study (aus diab) using a quantile regression approach. Article. Nutrients. 2019;11(8) | Outcome
354 | Gainfort A, Delahunt A, Killeen SL, Energy-Adjusted Dietary Inflammatory Index in pregnancy and maternal cardiometabolic health: findings from the ROLO study. Article. AJOG Glob Rep. May 2023;3(2):100214. doi:10.1016/j.xagr.2023.100214 37234814 | Intervention or Exposure
355 | Gajda R, Raczkowska E, Sobieszczanska M, Noculak L, Szymala-Pedzik M, Godyla-Jablonski M. Diet Quality Variation among Polish Older Adults: Association with Selected Metabolic Diseases, Demographic Characteristics and Socioeconomic Status. Int J Environ Res Public Health. Feb 7 2023;20(4)doi:10.3390/ijerph20042878 | Study design
356 | Galan-Lopez P, Dominguez R, Pihu M, Gisladottir T, Sanchez-Oliver AJ, Ries F. Evaluation of Physical Fitness, Body Composition, and Adherence to Mediterranean Diet in Adolescents from Estonia: The AdolesHealth Study. Int J Environ Res Public Health. Nov 14 2019;16(22)doi: 10.3390/ijerph16224479 | Study design
357 | Galan-Lopez P, Sanchez-Oliver AJ, Pihu M, Gisladottir T, Dominguez R, Ries F. Association between Adherence to the Mediterranean Diet and Physical Fitness with Body Composition Parameters in 1717 European Adolescents: The AdolesHealth Study. Nutrients. Dec 27 2019;12(1)doi:10.3390/nu12010077 | Study design
358 | Gallagher D, Rosenn B, Toro-Ramos T, Greater Neonatal Fat-Free Mass and Similar Fat Mass Following a Randomized Trial to Control Excess Gestational Weight Gain. Obesity (Silver Spring). Mar 2018;26(3):578–587. doi:10.1002/oby.22079 29464905 | Outcome
359 | Ganguli SC, Russell LA, Tsoi KS. Implementation of a Whole Food Plant Based Diet in a Food as Prevention Program in a Resource Constrained Environment. J Lifestyle Med. Sep 30 2022;12(3):148–152. doi:10.15280/jlm.2022.12.3.148 36628184 | Intervention or Exposure; Comparator
360 | Gans KM, Tovar A, Kang A, A multi-component tailored intervention in family childcare homes improves diet quality and sedentary behavior of preschool children compared to an attention control: results from the Healthy Start-Comienzos Sanos cluster randomized trial. Int J Behav Nutr Phys Act. Apr 15 2022;19(1):45. doi:10.1186/s12966-022-01272-6 35428298 | Intervention or Exposure; Outcome; Comparator
361 | Garcia-Mantrana I, Selma-Royo M, Gonzalez S, Parra-Llorca A, Martinez-Costa C, Collado MC. Distinct maternal microbiota clusters are associated with diet during pregnancy: impact on neonatal microbiota and infant growth during the first 18 months of life. Gut Microbes. Jul 3 2020;11(4):962–978. doi:10.1080/19490976.2020.1730294 32167021 | Intervention or Exposure; Comparator
362 | Gardea-Resendez M, Winham SJ, Romo-Nava F, Quantification of diet quality utilizing the rapid eating assessment for participants-shortened version in bipolar disorder: Implications for prospective depression and cardiometabolic studies. J Affect Disord. Aug 1 2022;310:150–155. doi: 10.1016/j.jad.2022.05.037 35545158 | Study design
363 | Gardner CD, Landry MJ, Perelman D, Effect of a ketogenic diet versus Mediterranean diet on glycated hemoglobin in individuals with prediabetes and type 2 diabetes mellitus: The interventional Keto-Med randomized crossover trial. Am J Clin Nutr. Sep 2 2022; 116(3):640–652. doi: 10.1093/ajcn/nqac154 35641199 | Intervention or Exposure - Foods/Beverages Not Reported
364 | Gardner CD, Landry MJ, Perelman D, Errartum/Correction: Effect of a ketogenic diet versus Mediterranean diet on glycated hemoglobin in individuals with prediabetes and type 2 diabetes mellitus: The interventional Keto-Med randomized crossover trial. Am J Clin Nutr. Sep 2 2022;116(3):640–652. doi:10.1093/ajcn/nqac279 35641199 | Intervention or Exposure - Foods/Beverages Not Reported
365 | Garland VF, Regunathan-Shenk R, Lew SQ. The plant-based diet, microbiome, and kidney health relationship. Journal of Kidney Care. 2021;6(3):112–118. | Study design; Publication status
366 | Garousi N, Tamizifar B, Pourmasoumi M, Effects of lacto-ovo-vegetarian diet vs. standard-weight-loss diet on obese and overweight adults with non-alcoholic fatty liver disease: a randomised clinical trial. Arch Physiol Biochem. Dec 2023;129(4):975–983. doi: 10.1080/13813455.2021.1890128 33689525 | Intervention or Exposure - Foods/Beverages Not Reported; Health Status
367 | Garr Barry V, Stewart M, Soleymani T, Desmond RA, Goss AM, Gower BA. Greater Loss of Central Adiposity from Low-Carbohydrate versus Low-Fat Diet in Middle-Aged Adults with Overweight and Obesity. Nutrients. Jan 31 2021;13(2)doi: 10.3390/nu13020475 | Intervention or Exposure - Foods/Beverages Not Reported
368 | Garralda-Del-Villar M, Carlos-Chilleron S, Diaz-Gutierrez J, Healthy Lifestyle and Incidence of Metabolic Syndrome in the SUh Cohort. Article. Nutrients. Dec 30 2018;11(1)doi:10.3390/nu11010065 | Intervention or Exposure; Outcome
369 | Gautreaux CE, Smith KS, Dolan L, Early Pandemic Improvements in Diet Quality Are Associated with Increased Physical Activity and Weight Loss in US Adults. Article. Int J Environ Res Public Health. Jul 7 2022;19(14)doi:10.3390/ijerph19148289 | Study design
370 | Geiker NRW, Magkos F, Zingenberg H, A high-protein low-glycemic index diet attenuates gestational weight gain in pregnant women with obesity: the "An optimized programming of healthy children" (APPROACH) randomized controlled trial. Article. Am J Cl Nutr. Mar 4 2022;115(3):970–979. doi:10.1093/ajcn/nqab405 | Intervention or Exposure
371 | Genis B, Kayalar A, Donmez A, Cosar B. Effect of Structured Cognitive-Behavioral Group Therapy on Body Weight, Mental Status and the Quality of Life in Obese and Overweight Individuals: A 16-Week Follow Up Study. Article. Turk Psikiyatri Derg. Spring 2022;33(1):11–21. Obez ve Asiri Kilolu Bireylerde Yapilandirilmis Bilissel Davranisci Grup Terapisinin Vucut Agirligi, Ruhsal Durum ve Yasam Kalitesi Uzerine Etkisi: 16 Haftalik Bir Takip Calismasi. doi:10.5080/u25606 | Study design; Intervention or Exposure
372 | Genoni G, Menegon V, Monzani A, Healthy Lifestyle Intervention and Weight Loss Improve Cardiovascular Dysfunction in Children with Obesity. Nutrients. Apr 15 2021;13(4)doi:10.3390/nu13041301 | Study design
373 | George SA, Kumar N. A study of evaluation of body mass index and food pattern changes in patients undergoing orthodontic treatment. Article. Drug Invention Today. 2019;12:68–70. | Study design
374 | Georgoulis M, Chrysohoou C, Georgousopoulou E, Long-term prognostic value of LDL-C, HDL-C, lp(a) and TG levels on cardiovascular disease incidence, by body weight status, dietary habits and lipid-lowering treatment: the ATTICA epidemiological cohort study (2002–2012). Lipids Health Dis. Dec 19 2022;21(1):141. doi:10.1186/s12944-022-01747-2 36529737 | Intervention or Exposure
375 | Georgoulis M, Georgousopoulou EN, Chrysohoou C, Pitsavos C, Panagiotakos DB. Longitudinal Trends, Determinants, and Cardiometabolic Impact of Adherence to the Mediterranean Diet among Greek Adults. Foods. Aug 9 2022;11(16)doi:10.3390/foods11162389 | Intervention or Exposure; Outcome
376 | Georgoulis M, Yiannakouris N, Kechribari I, Dose-response relationship between weight loss and improvements in obstructive sleep apnea severity after a diet/lifestyle interventions: secondary analyses of the "MIMOSA" randomized clinical trial. J Clin Sleep Med. May 1 2022;18(5):1251–1261. doi:10.5664/jcsm.9834 34915980 | Intervention or Exposure; Outcome; Comparator
377 | Gepner Y, Shelef I, Komy O, The beneficial effects of Mediterranean diet over low-fat diet may be mediated by decreasing hepatic fat content. Clinical Trial, Phase I; Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. J Hepatol. Aug 2019;71(2):379–388. doi: 10.1016/j.jhep.2019.04.013 31075323 | Intervention or Exposure - Foods/Beverages Not Reported
378 | Gete DG, Waller M, Mishra GD. Prepregnancy dietary patterns and risk of preterm birth and low birth weight: findings from the Australian Longitudinal Study on Women's Health. Am J Clin Nutr. May 1 2020;111(5): 1048–1058. doi:10.1093/ajcn/nqaa057 32282895 | Outcome
379 | Ghomari L, Ghomari-Boukhatem H, Raiah M, Boukhari Y, Bouchenak M. Lifestyle, Cardiometabolic and Inflammatory markers in Schoolchildren and their Associations with Body Mass Index. Article. Progress in Nutrition. 2022;24(3)doi:10.23751/pn.v24i3.12027 | Study design
380 | Gianfredi V, Bertarelli G, Minelli L, Nucci D. Promoting healthy eating in childhood: results from the Children PrOmOting Nutrition through Theatre (COcONUT) project. Minerva Pediatr (Torino). Aug 2024;76(4):464–472. doi:10.23736/S2724-5276.21.06249-2 33861050 | Outcome
381 | Giardina S, Hernandez-Alonso P, Diaz-Lopez A, Salas-Huetos A, Salas-Salvado J, Bullo M. Changes in circulating miRNAs in healthy overweight and obese subjects: Effect of diet composition and weight loss. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Clin Nutr. Feb 2019;38(1):438–443. doi: 10.1016/j.clnu.2017.11.014 29233588 | Intervention or Exposure - Foods/Beverages Not Reported
382 | Gibbs BB, Tudorascu D, Bryce CL, Lifestyle Habits Associated with Weight Regain After Intentional Loss in Primary Care Patients Participating in a Randomized Trial. Article. J Gen Intern Med. Nov 2020;35(11):3227–3233. doi: 10.1007/s11606-020-06056-x 32808209 | Intervention or Exposure
383 | Gil-Campos M, Perez-Ferreiros A, Llorente-Cantarero FJ, Association of Diet, Physical Activity Guidelines and Cardiometabolic Risk Markers in Children. Nutrients. Aug 25 2021;13(9)doi:10.3390/nu13092954 | Study design
384 | Giontella A, Bonafini S, Tagetti A, Relation between Dietary Habits, Physical Activity, and Anthropometric and Vascular Parameters in Children Attending the Primary School in the Verona South District. Article. Nutrients. May 14 2019;11(5)doi:10.3390/nu11051070 | Study design
385 | Gkouskou KG, Georgiopoulos G, Vlastos I, CYP1A2 polymorphisms modify the association of habitual coffee consumption with appetite, macronutrient intake, and body mass index: results from an observational cohort and a cross-over randomized study. Int J Obes (Lond). Jan 2022;46(1):162–168. doi:10.1038/s41366-021-00972-6 34564706 | Intervention or Exposure
386 | Glenn AJ, Li J, Lo K, The Portfolio Diet and Incident Type 2 Diabetes: Findings From the Women's Health Initiative Prospective Cohort Study. Diabetes Care. Jan 1 2023;46(1):28–37. doi:10.2337/dc22-1029 36162007 | Outcome
387 | Glud M, Christiansen T, Larsen LH, Richelsen B, Bruun JM. Changes in Circulating BDNF in relation to Sex, Diet, and Exercise: A 12-Week Randomized Controlled Study in Overweight and Obese Participants. J Obes. 2019;2019:4537274. doi: 10.1155/2019/4537274 31781387 | Intervention or Exposure - Foods/Beverages Not Reported
388 | Goetz AR, Jindal I, Moreno JP, The roles of sleep and eating patterns in adiposity gain among preschool-aged children. Am J Clin Nutr. Nov 2022;116(5):1334–1342. doi:10.1093/ajcn/nqac197 35833269 | Intervention or Exposure
389 | Goff LM, Huang P, Silva MJ, Associations of dietary intake with cardiometabolic risk in a multi-ethnic cohort: a longitudinal analysis of the Determinants of Adolescence, now young Adults, Social well-being and Health (DASH) study. Article. Br J Nutr. May 2019; 121 (9): 1069–1079. doi:10.1017/S0007114519000291 30764887 | Intervention or Exposure
390 | Goldenshluger A, Constantini K, Goldstein N, Effect of Dietary Strategies on Respiratory Quotient and Its Association with Clinical Parameters and Organ Fat Loss: A Randomized Controlled Trial. Nutrients. Jun 29 2021;13(7)doi:10.3390/nu13072230 | Intervention or Exposure - Foods/Beverages Not Reported
391 | Golzarand M, Moslehi N, Mirmiran P, Azizi F. Adherence to the DASH, MeDi, and MIND diet scores and the incidence of metabolically unhealthy phenotypes. Obes Res Clin Pract. May-Jun 2023;17(3):226–232. doi:10.1016/j.orcp.2023.04.001 37037714 | Outcome
392 | Gomez-Huelgas R, Ruiz-Nava J, Santamaria-Fernandez S, Impact of Intensive Lifestyle Modification on Levels of Adipokines and Inflammatory Biomarkers in Metabolically Healthy Obese Women. Article. Mediators Inflamm. 2019;2019:4165260. doi:10.1155/2019/4165260 31093012 | Study design; Outcome
393 | Gontijo CA, Balieiro LCT, Teixeira GP, Fahmy WM, Crispim CA, Maia YCP. Effects of timing of food intake on eating patterns, diet quality and weight gain during pregnancy. Br J Nutr. Apr 28 2020;123(8):922–933. doi:10.1017/S0007114519003398 31902384 | Intervention or Exposure; Comparator
394 | Gonzalez-Nahm S, Marchesoni J, Maity A, Maternal Mediterranean Diet Adherence and Its Associations with Maternal Prenatal Stressors and Child Growth. Curr Dev Nutr. Nov 2022;6(11):nzac146. doi:10.1093/cdn/nzac146 36406812 | Outcome
395 | Gonzalez-Nahm S, Mendez M, Robinson W, Low maternal adherence to a Mediterranean diet is associated with increase in methylation at the MEG3-IG differentially methylated region in female infants. Environ Epigenet. May 2017;3(2):dvx007. doi: 10.1093/eep/dvx007 29492309 | Outcome
396 | Goswami N, Trozic I, Fredriksen MV, Fredriksen PM. The effect of physical activity intervention and nutritional habits on anthropometric measures in elementary school children: the health oriented pedagogical project (HOPP). Int J Obes (Lond). Aug 2021;45(8): 1677–1686. doi:10.1038/s41366-021-00830-5 33972698 | Intervention or Exposure; Comparator
397 | Gow ML, Lam YWI, Jebeile H, Craig ME, Susie D, Henry A. Antenatal diet quality and perinatal depression: the Microbiome Understanding in Maternity Study (MUMS) cohort. J Hum Nutr Diet. Jun 2023;36(3):754–762. doi: 10.1111/jhn.13081 36106616 | Outcome
398 | Gow ML, Lam YWI, Jebeile H, Craig ME, Susie D, Henry A. Antenatal diet quality and perinatal depression: the MUMS cohort. J Hum Nutr Diet. Jun 2023;36(3):754–762. doi:10.1111/jhn.13081 36106616 | Outcome
399 | Grammatikopoulou MG, Nigdelis MP, Haidich AB, Diet Quality and Nutritional Risk Based on the FIGO Nutrition Checklist among Greek Pregnant Women: A Cross-Sectional Routine Antenatal Care Study. Article. Nutrients. Apr 22 2023;15(9)doi:10.3390/nu15092019 | Study design
400 | Grams L, Nelius AK, Pastor GG, Comparison of Adherence to Mediterranean Diet between Spanish and German School-Children and Influence of Gender, Overweight, and Physical Activity. Nutrients. Nov 7 2022;14(21)doi:10.3390/nu14214697 | Study design
401 | Granic A, Mendonca N, Sayer AA, Effects of dietary patterns and low protein intake on sarcopenia risk in the very old: The Newcastle 85+ study. Clin Nutr. Jan 2020;39(1): 166–173. doi:10.1016/j.clnu.2019.01.009 30709690 | Outcome
402 | Granziera F, Guzzardi MA, lozzo P. Associations between the Mediterranean Diet Pattern and Weight Status and Cognitive Development in Preschool Children. Article. Nutrients. Oct 22 2021;13(11 )doi:10.3390/nu13113723 | Intervention or Exposure; Outcome
403 | Gray KL, Clifton PM, Keogh JB. The effect of intermittent energy restriction on weight loss and diabetes risk markers in women with a history of gestational diabetes: a 12-month randomized control trial. Am J Clin Nutr. Aug 2 2021;114(2):794–803. doi: 10.1093/ajcn/nqab058 33831950 | Intervention or Exposure
404 | Gray KL, Clifton PM, Keogh JB. Weight Loss Barriers and Dietary Quality of Intermittent and Continuous Dieters in Women with a History of Gestational Diabetes. Article. Int J Environ Res Public Health. Sep 29 2021;18(19)doi: 10.3390/ijerph181910243 | Outcome
405 | Gray ME, Bae S, Ramachandran R, Dietary Patterns and Prevalent NAFLD at Year 25 from the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Nutrients. Feb 18 2022;14(4)doi:10.3390/nu14040854 | Outcome
406 | Greathouse KL, Padgett RN, Petrosino J, Hastings-Tolsma M, Faucher MA. Exploration of Diet Quality by Obesity Severity in Association with Gestational Weight Gain and Distal Gut Microbiota in Pregnant African American Women: Opportunities for Intervention. Article in Press. Matern Child Health J. Apr 2022;26(4):882–894. doi:10.1007/s10995-021-03198-0 34462812 | Outcome
407 | Grech A, Rangan A, Allman-Farinelli M, Simpson SJ, Gill T, Raubenheimer D. A Comparison of the Australian Dietary Guidelines to the NOVA Classification System in Classifying Foods to Predict Energy Intakes and Body Mass Index. Nutrients. Sep 23 2022;14(19)doi:10.3390/nu14193942 | Study design
408 | Griauzde DH, Lumeng JC, Shah PE, Kaciroti N. Lower Body Mass Index Z-Score Trajectory During Early Childhood After the Birth of a Younger Sibling. Article. Acad Pediatr. Jan-Feb 2019;19(1):51–57. doi:10.1016/j.acap.2018.06.003 29920332 | Intervention or Exposure
409 | Guedes MR, Fittipaldi-Fernandez RJ, Diestel CF, Klein M. Changes in Body Adiposity, Dietary Intake, Physical Activity and Quality of Life of Obese Individuals Submitted to Intragastric Balloon Therapy for 6 Months. Article. Obes Surg. Mar 2019;29(3):843–850. doi: 10.1007/s11695-018-3609-x 30536199 | Health Status- 100% Hospitalized/Surgical
410 | Gunther J, Hoffmann J, Spies M, Associations between the prenatal diet and neonatal outcomesa€”a secondary analysis of the cluster-randomised gelis trial. Journal: Article. Nutrients. 2019;11(8) | Outcome; Comparator
411 | Habib-Mourad C, Ghandour LA, Maliha C, Dagher M, Kharroubi S, Hwalla N. Impact of a Three-Year Obesity Prevention Study on Healthy Behaviors and BMI among Lebanese Schoolchildren: Findings from Ajyal Salima Program. Nutrients. Sep 3 2020;12(9)doi:10.3390/nu12092687 | Intervention or Exposure
412 | Haddad EN, Nel NH, Petrick LM, Kerver JM, Comstock SS. Associations between the Gut Microbiota, Urinary Metabolites, and Diet in Women during the Third Trimester of Pregnancy. Article. Curr Dev Nutr. Apr 2023;7(4):100025. doi:10.1016/j.cdnut.2022.100025 37304851 | Study design; Intervention or Exposure - Foods/Beverages Not Reported; Outcome
413 | Hadi A, Hasani H, Kafeshani M. The Effect of DASH Diet on Anthropometric Indices and Body Composition in Healthy Obese Wome. Academic Journal. Com university of medical sciences journal. 2019;13(3):14–16. | Language
414 | Hafez Griauzde D, Saslow L, Patterson K, Mixed methods pilot study of a low-carbohydrate diabetes prevention programme among adults with pre-diabetes in the USA. BMJ Open. Jan 21 2020;10(1):e033397. doi: 10.1136/bmjopen-2019-033397 | Study design
415 | Haghighat N, Ashtary-Larky D, Bagheri R, Corrigendum: The effect of 12 weeks of euenergetic high-protein diet in regulating appetite and body composition of women with normal-weight obesity: a randomised controlled trial. Br J Nutr. 2020. 124(10):1044–1051.2021;126:959–959.32513334 | Publication status; Intervention or Exposure - Foods/Beverages Not Reported
416 | Haghighat N, Ashtary-Larky D, Bagheri R, Effects of 6 Months of Soy-Enriched High Protein Compared to Eucaloric Low Protein Snack Replacement on Appetite, Dietary Intake, and Body Composition in Normal-Weight Obese Women: A Randomized Controlled Trial. Nutrients. Jun 30 2021;13(7)doi:10.3390/nu13072266 | Intervention or Exposure
417 | Haghighat N, Ashtary-Larky D, Bagheri R, The effect of 12 weeks of euenergetic high-protein diet in regulating appetite and body composition of women with normal-weight obesity: a randomised controlled trial. Br J Nutr. Nov 28 2020;124(10):1044–1051. doi: 10.1017/S0007114520002019 32513334 | Intervention or Exposure - Foods/Beverages Not Reported
418 | Hailili G, Chen Z, Tian T, Dietary patterns and their associations with the metabolic syndrome and predicted 10-year risk of CVD in northwest Chinese adults. Article. Br J Nutr. Sep 28 2021;126(6):913–922. doi:10.1017/S000711452000478X 33256885 | Outcome
419 | Hajihashemi P, Hassannejad R, Haghighatdoost F, The long-term association of different dietary protein sources with metabolic syndrome. Article. Sci Rep. Sep 29 2021;11(1):19394. doi:10.1038/s41598-021-98688-0 34588516 | Intervention or Exposure; Outcome
420 | Hall WL. The emerging importance of tackling sleep-diet interactions in lifestyle interventions for weight management. Br J Nutr. Aug 14 2022;128(3):561–568. doi: 10.1017/S000711452200160X 35603425 | Study design
421 | HAIWattar B, Dodds J, Placzek A, Mediterranean-style diet in pregnant women with metabolic risk factors (ESTEEM): A pragmatic multicentre randomised trial. Journal Article; Multicenter Study; Pragmatic Clinical Trial; Research Support, Non-U.S. Gov't. PLoS Med. Jul 2019;16(7):e1002857. doi:10.1371/journal.pmed.1002857 31335871 | Data overlap
422 | Hammons AJ, Hannon BA, Teran-Garcia M, Effects of Culturally Tailored Nutrition Education on Dietary Quality of Hispanic Mothers: A Randomized Control Trial. J Nutr Educ Behav. Nov-Dec 2019;51(10):1168–1176. doi:10.1016/j.jneb.2019.06.017 31375361 | Intervention or Exposure; Duration of Intervention; Outcome
423 | Han L, Zhang T, You D, Temporal and mediation relations of weight loss, and changes in insulin resistance and blood pressure in response to 2-year weight-loss diet interventions: the POUNDS Lost trial. Article. Eur J Nutr. Feb 2022;61(1):269–275. doi: 10.1007/S00394-021-02643-8 34319427 | Intervention or Exposure
424 | Han Y, Kang D, Lee SA. Effect of 'rice' pattern on high blood pressure by gender and obesity: using the community-based KoGES cohort. Public Health Nutr. Feb 2020;23(2):275–285. doi:10.1017/S136898001900168X 31280733 | Outcome
425 | Hanafiah AN, Aagaard-Hansen J, Ch Cheah J, Effectiveness of a complex, pre-conception intervention to reduce the risk of diabetes by reducing adiposity in young adults in Malaysia: The Jom Mama project - A randomised controlled trial. J Glob Health. Aug 17 2022;12:04053. doi:10.7189/jogh.12.04053 35972832 | Intervention or Exposure
426 | Handakas E, Chang K, Khandpur N, Metabolic profiles of ultra-processed food consumption and their role in obesity risk in British children. Clin Nutr. Nov 2022;41(11):2537–2548. doi:10.1016/j.clnu.2022.09.002 36223715 | Outcome
427 | Hansen TT, Mead BR, Garcia-Gavilan JF, Is reduction in appetite beneficial for body weight management in the context of overweight and obesity? Yes, according to the SATIN (Satiety Innovation) study. J Nutr Sci. Nov 27 2019;8:e39. doi: 10.1017/jns.2019.36 32042406 | Intervention or Exposure
428 | Hao L, Jiang H, Zhang B, High Diet Quality Is Linked to Low Risk of Abdominal Obesity among the Elderly Women in China. Article. Nutrients. Jun 24 2022;14(13)doi:10.3390/nu14132623 | Country
429 | Harbers MC, de Kroon AM, Boer JMA, Adherence to the Dutch dietary guidelines and 15-year incidence of heart failure in the EPIC-NL cohort. Article. Eur J Nutr. Dec 2020;59(8):3405–3413. doi: 10.1007/s00394-019-02170-7 31912232 | Outcome
430 | Harbury C, Collins CE, Callister R. Diet quality is lower among adults with a BMI >/=40kgm(-2) or a history of weight loss surgery. Article. Obes Res Clin Pract. Mar-Apr 2019;13(2):197–204. doi: 10.1016/j.orcp.2018.10.003 30409499 | Study design
431 | Hardy DS, Racette SB, Garvin JT, Gebrekristos HT, Mersha TB. Ancestry specific associations of a genetic risk score, dietary patterns and metabolic syndrome: a longitudinal ARIC study. BMC Med Genomics. May 1 2021;14(1):118. doi:10.1186/s12920-021-00961-8 33933074 | Outcome
432 | Harreiter J, Simmons D, Desoye G, Nutritional Lifestyle Intervention in Obese Pregnant Women, Including Lower Carbohydrate Intake, Is Associated With Increased Maternal Free Fatty Acids, 3-beta-Hydroxybutyrate, and Fasting Glucose Concentrations: A Secondary Factorial Analysis of the European Multicenter, Randomized Controlled DALI Lifestyle Intervention Trial. Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Diabetes Care. Aug 2019;42(8):1380–1389. doi:10.2337/dc19-0418 31182492 | Intervention or Exposure; Data overlap
433 | Hartmann AM, Dell'Oro M, Spoo M, To eat or not to eat-an exploratory randomized controlled trial on fasting and plant-based diet in rheumatoid arthritis (NutriFast-Study). Front Nutr. 2022;9:1030380. doi:10.3389/fnut.2022.1030380 36407522 | Intervention or Exposure - Foods/Beverages Not Reported; Health Status
434 | Hasain Z, Raja Ali RA, Abdul Razak S, Gut Microbiota Signature Among Asian Post-gestational Diabetes Women Linked to Macronutrient Intakes and Metabolic Phenotypes. Front Microbiol. 2021;12:680622. doi:10.3389/fmicb.2021.680622 34248897 | Study design
435 | Hassan BK, Cunha DB, Santos RO, Baltar VT. Breakfast patterns and weight status among adolescents: a study on the Brazilian National Dietary Survey 2008–2009. Br J Nutr. May 28 2022;127(10):1549–1556. doi:10.1017/S0007114521002403 34180382 | Study design; Intervention or Exposure
436 | Hata T, Seino S, Yokoyama Y, Interaction of Eating Status and Dietary Variety on Incident Functional Disability among Older Japanese Adults. Article. J Nutr Health Aging. 2022;26(7):698–705. doi:10.1007/s12603-022-1817-5 35842760 | Intervention or Exposure; Outcome
437 | Havas Augustin D, Sarac J, Lovric M, Adherence to Mediterranean Diet and Maternal Lifestyle during Pregnancy: Island-Mainland Differentiation in the CRIBS Birth Cohort. Nutrients. Jul 22 2020;12(8)doi:10.3390/nu12082179 | Outcome
438 | Hazrati Gonbad S, Zakerimoghadam M, Pashaeypoor S, Haghani S. The Effects of Home-Based Self-Care Education on Blood Pressure and Self-Care Behaviors among Middle-Aged Patients with Primary Hypertension in Iran: A Randomized Clinical Controlled Trial. Home Health Care Management & Practice. 2022;34(1):9–16. | Intervention or Exposure; Duration of Intervention
439 | He D, Qiao Y, Xiong S, Liu S, Ke C, Shen Y. Association between Dietary Quality and Prediabetes based on the Diet Balance Index. Sci Rep. Feb 21 2020;10(1):3190. doi:10.1038/s41598-020-60153-9 32081975 | Study design; Outcome; Country
440 | He M, Wang J, Liang Q, Time-restricted eating with or without low-carbohydrate diet reduces visceral fat and improves metabolic syndrome: A randomized trial. Cell Rep Med. Oct 18 2022;3(10):100777. doi: 10.1016/j.xcrm.2022.100777 36220069 | Study design; Intervention or Exposure - Foods/Beverages Not Reported; Comparator
441 | He Y, Fang Y, Bromage S, Application of the Global Diet Quality Score in Chinese Adults to Evaluate the Double Burden of Nutrient Inadequacy and Metabolic Syndrome. J Nutr. Oct 23 2021;151(12 Suppl 2):93S–100S. doi:10.1093/jn/nxab162 34689199 | Study design
442 | He YM, Chen WL, Kao TW, Wu LW, Yang HF, Peng TC. Relationship between Ideal Cardiovascular Health and Incident Proteinuria: A 5 Year Retrospective Cohort Study. Nutrients. Sep 28 2022;14(19)doi:10.3390/nu14194040 | Outcome; Country
443 | Heianza Y, Zhou T, Sun D, Hu FB, Qi L. Healthful plant-based dietary patterns, genetic risk of obesity, and cardiovascular risk in the UK biobank study. Clin Nutr. Jul 2021;40(7):4694–4701. doi:10.1016/j.clnu.2021.06.018 34237696 | Study design
444 | Hengeveld LM, Wijnhoven HAH, Olthof MR, Prospective Associations of Diet Quality With Incident Frailty in Older Adults: The Health, Aging, and Body Composition Study. Article. J Am Geriatr Soc. Sep 2019;67(9): 1835–1842. doi: 10.1111/jgs.16011 31267522 | Outcome
445 | Henning SM, Yang J, Woo SL, Hass Avocado Inclusion in a Weight-Loss Diet Supported Weight Loss and Altered Gut Microbiota: A 12-Week Randomized, Parallel-Controlled Trial. Journal: Article. Curr Dev Nutr. Aug 2019;3(8):nzz068. doi: 10.1093/cdn/nzz068 31367691 | Intervention or Exposure; Comparator
446 | Henriques HKF, Fonseca LM, de Andrade KS, Gluten-Free Diet Reduces Diet Quality and Increases Inflammatory Potential in Non-Celiac Healthy Women. J Am Nutr Assoc. Nov-Dec 2022;41(8)771–779. doi:10.1080/07315724.2021.1962769 34516338 | Duration of Intervention
447 | Hernaez A, Lassale C, Castro-Barquero S, Mediterranean diet maintained platelet count within a healthy range and decreased thrombocytopenia-related mortality risk: A randomized controlled trial. Article. Nutrients. 2021;13(2):1–13. | Intervention or Exposure; Outcome
448 | Hernandez-Reyes A, Camara-Martos F, Molina-Luque R, Romero-Saldana M, Molina-Recio G, Moreno-Rojas R. Changes in body composition with a hypocaloric diet combined with sedentary, moderate and high-intense physical activity: a randomized controlled trial. Journal Article; Randomized Controlled Trial. BMC Womens Health. Dec 27 2019;19(1):167. doi: 10.1186/s12905-019-0864-5 31882009 | Intervention or Exposure; Comparator
449 | Hernando-Redondo J, Toloba A, Benaiges D, Mid- and long-term changes in satiety-related hormones, lipid and glucose metabolism, and inflammation after a Mediterranean diet intervention with the goal of losing weight: A randomized, clinical trial. Front Nutr. 2022;9:950900. doi:10.3389/fnut.2022.950900 36466401 | Intervention or Exposure; Comparator
450 | Herrera-Espineira C, Martinez-Cirre MDC, Lopez-Morales M, Hospital Intervention to Reduce Overweight with Educational Reinforcement after Discharge: A Multicenter Randomized Clinical Trial. Article. Nutrients. Jun 16 2022;14(12)doi:10.3390/nu14122499 | Intervention or Exposure; Health Status- 100% Hospitalized/Surgical
451 | Herrera-Quintana L, Vazquez-Lorente H, Carranco Romo MJ, Imbalanced dietary patterns, anthropometric, and body composition profiles amongst adults with Down syndrome. Nutr Neurosci. Feb 2024;27(2):96–105. doi: 10.1080/1028415X.2022.2161139 36579765 | Study design
452 | Heslehurst N, Flynn AC, Ngongalah L, Diet, Physical Activity and Gestational Weight Gain Patterns among Pregnant Women Living with Obesity in the North East of England: The GLOWING Pilot Trial. Article. Nutrients. Jun 9 2021;13(6)doi: 10.3390/nu13061981 | Intervention or Exposure
453 | Hezaveh ZS, Feizy Z, Dehghani F, Sarbakhsh P, Moini A, Vafa M. The Association between Maternal Dietary Protein Intake and Risk of Gestational Diabetes Mellitus. Int J Prev Med. 2019;10:197. doi:10.4103/ijpvm.UPVM_86_19 31772729 | Study design; Intervention or Exposure
454 | Higuera-Gomez A, Ribot-Rodriguez R, Mico V, Cuevas-Sierra A, San Cristobal R, Martinez JA. Lifestyle and Health-Related Quality of Life Relationships Concerning Metabolic Disease Phenotypes on the Nutrimdea Online Cohort. Int J Environ Res Public Health. Dec 31 2022;20(1)doi:10.3390/ijerph20010767 | Study design
455 | Higurashi S, Tsujimori Y, Nojiri K, Toba Y, Nomura K, Ueno HM. Dietary Patterns Associated with General Health of Breastfeeding Women 1–2 Months Postpartum: Data from the Japanese Human Milk Study Cohort. Article. Curr Dev Nutr. Jan 2023;7(1):100004. doi: 10.1016/j.cdnut.2022.100004 37181129 | Study design; Outcome
456 | Hill E, Hodge A, Clifton P, Longitudinal nutritional changes in aging Australian women. Article. Asia Pac J Clin Nutr. 2019;28(1):139–149. doi:10.6133/apjcn.201903_28(1).0019 30896425 | Size or Power
457 | Hill EB, Cubellis LT, Wexler RK, Taylor CA, Spees CK. Differences in Adherence to American Heart Association's Life's Essential 8, Diet Quality, and Weight Loss Strategies Between Those With and Without Recent Clinically Significant Weight Loss in a Nationally Representative Sample of US Adults. J Am Heart Assoc. Apr 18 2023;12(8):e026777. doi: 10.1161/JAHA.122.026777 37026539 | Study design
458 | Hirko KA, Comstock SS, Strakovsky RS, Kerver JM. Diet during Pregnancy and Gestational Weight Gain in a Michigan Pregnancy Cohort. Curr Dev Nutr. Aug 2020;4(8):nzaa121. doi:10.1093/cdn/nzaa121 32793851 | Intervention or Exposure
459 | Hjorth MF, Bray GA, Zohar Y, Pretreatment Fasting Glucose and Insulin as Determinants of Weight Loss on Diets Varying in Macronutrients and Dietary Fibers-The POUNDS LOST Study. Article. Nutrients. Mar 11 2019;11(3)doi:10.3390/nu11030586 | Intervention or Exposure - Foods/Beverages Not Reported
460 | Hjorth MF, Corella D, Astrup A, High fat diets for weight loss among subjects with elevated fasting glucose levels: the PREDIMED study. Journal: Article. Obesity medicine. 2020;18 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
461 | Hjorth T, Huseinovic E, Hallstrom E, Changes in dietary carbon footprint over ten years relative to individual characteristics and food intake in the Vasterbotten Intervention Programme. Article. Sci Rep. Jan 8 2020;10(1):20. doi:10.1038/s41598-019-56924-8 31913331 | Intervention or Exposure
462 | Hobbs M, Green M, Roberts K, Griffiths C, McKenna J. Reconsidering the relationship between fast-food outlets, area-level deprivation, diet quality and body mass index: an exploratory structural equation modelling approach. Article. J Epidemiol Community Health. Sep 2019;73(9):861–866. doi:10.1136/jech-2018-211798 31171581 | Study design; Intervention or Exposure
463 | Hodge AM, Karim MN, Hebert JR, Shivappa N, de Courten B. Association between Diet Quality Indices and Incidence of Type 2 Diabetes in the Melbourne Collaborative Cohort Study. Nutrients. Nov 20 2021;13(11)doi:10.3390/nu13114162 | Outcome
464 | Hoffmann A, Meir AY, Hagemann T, A polyphenol-rich green Mediterranean diet enhances epigenetic regulatory potential: the DIRECT PLUS randomized controlled trial. Metabolism. Aug 2023;145:155594. doi:10.1016/j.metabol.2023.155594 37236302 | Intervention or Exposure
465 | Holmes H, Palacios C, Wu Y, Banna J. Effect of a Short Message Service Intervention on Excessive Gestational Weight Gain in a Low-Income Population: A Randomized Controlled Trial. Nutrients. May 15 2020;12(5)doi:10.3390/nu12051428 | Intervention or Exposure
466 | Hotowko-Ziółek J, Cięszczyk P, Biliński J, Basak GW, Stachowska E. What Model of Nutrition Can Be Recommended to People Ending Their Professional Sports Career? An Analysis of the Mediterranean Diet and the CRON Diet in the Context of Former Athletes. Nutrients. 2020;12(12):3604.33255295 | Study design
467 | Hopkins LC, Tiba S, Westrick M, Gunther C. The Diet Quality of a Sample of Predominantly Racial Minority Children From Low-Income Households Is Lower During the Summer vs School Year: Results From the Project Summer Weight and Environmental Assessment Trial Substudy. J Acad Nutr Diet. Jan 2021;121(1):112–120. doi:10.1016/j.jand.2020.06.013 32800759 | Outcome
468 | Hosseini-Esfahani F, Koochakpoor G, Mirmiran P, Daneshpour MS, Azizi F. Dietary patterns modify the association between fat mass and obesity-associated genetic variants and changes in obesity phenotypes. Article. Br J Nutr. Jun 2019;121(11):1247–1254. doi:10.1017/S0007114519000643 30929646 | Country; Comparator
469 | Hosseini-Esfahani F, Koochakpoor G, Mirmiran P, Ebrahimof S, Azizi F. The association of dietary macronutrients with anthropometric changes, using iso-energetic substitution models: Tehran lipid and glucose study. Nutr Metab (Lond). 2019;16:83. doi: 10.1186/s12986-019-0411-2 31798665 | Intervention or Exposure
470 | Hosseinpour-Niazi S, Mirmiran P, Hadaegh F, Improvement of glycemic indices by a hypocaloric legume-based DASH diet in adults with type 2 diabetes: a randomized controlled trial. Eur J Nutr. Sep 2022;61(6):3037–3049. doi:10.1007/s00394-022-02869-0 35347394 | Health Status- 100% Diabetes
471 | Hu B, Tang S, Wang Z, Dietary diversity is associated with nutrient adequacy, blood biomarkers and anthropometric status among preschool children in poor ethnic minority area of Northwest China. Front Nutr. Nov 24 2022;9:948555. doi: 10.3389/fnut.2022.948555 36505258 | Study design
472 | Hu EA, Nguyen V, Langheier J, Shurney D. Weight Reduction Through a Digital Nutrition and Food Purchasing Platform Among Users With Obesity: Longitudinal Study. J Med Internet Res. Sep 2 2020;22(9):e19634. doi:10.2196/19634 32792332 | Intervention or Exposure
473 | Hu J, Aris IM, Lin PD, Association of Maternal Dietary Patterns during Pregnancy and Offspring Weight Status across Infancy: Results from a Prospective Birth Cohort in China. Article. Nutrients. Jun 15 2021;13(6)doi:10.3390/nu13062040 | Outcome
474 | Hu J, Li L, Wan N, Associations of Dietary Patterns during Pregnancy with Gestational Hypertension: The "Born in Shenyang" Cohort Study. Nutrients. Oct 17 2022;14(20)doi:10.3390/nu14204342 | Outcome
475 | Hu TY, Lee SY, Shih CK, Soluble CD163-Associated Dietary Patterns and the Risk of Metabolic Syndrome. Article. Nutrients. Apr 25 2019;11(4)doi:10.3390/nu11040940 | Study design
476 | Hu Z, Tylavsky FA, Kocak M, Effects of Maternal Dietary Patterns during Pregnancy on Early Childhood Growth Trajectories and Obesity Risk: The CANDLE Study. Nutrients. Feb 13 2020;12(2)doi:10.3390/nu12020465 | Outcome
477 | Huang CH, Okada K, Matsushita E, Dietary Patterns and Muscle Mass, Muscle Strength, and Physical Performance in the Elderly: A 3-Year Cohort Study. J Nutr Health Aging. 2021;25(1):108–115. doi:10.1007/s12603-020-1437-x 33367470 | Size or Power
478 | Huang JH, Li RH, Huang SL, Sia HK, Hsu WT, Tang FC. Health-Associated Nutrition and Exercise Behaviors in Relation to Metabolic Risk Factors Stratified by Body Mass Index. Article. Int J Environ Res Public Health. Mar 9 2019;16(5)doi:10.3390/ijerph16050869 | Study design
479 | Huang L, Wang H, Wang Z, Zhang J, Zhang B, Ding G. Regional Disparities in the Association between Cereal Consumption and Metabolic Syndrome: Results from the China Health and Nutrition Survey. Article. Nutrients. Apr 1 2019; 11 (4): 1–16. doi:10.3390/nu11040764 | Intervention or Exposure; Country
480 | Huang RC, Silva D, Beilin L, Feasibility of conducting an early pregnancy diet and lifestyle e-health intervention: the Pregnancy Lifestyle Activity Nutrition (PLAN) project. J Dev Orig Health Dis. Feb 2020;11(1):58–70. doi: 10.1017/S2040174419000400 31391133 | Intervention or Exposure - Foods/Beverages Not Reported
481 | Huang Z, Li N, Hu YM. Dietary patterns and their effects on postpartum weight retention of lactating women in south central China. Nutrition. Nov-Dec 2019;67–68:110555. doi: 10.1016/j.nut.2019.110555 | Study design
482 | Hudson JL, Zhou J, Campbell WW. Adults Who Are Overweight or Obese and Consuming an Energy-Restricted Healthy US-Style Eating Pattern at Either the Recommended or a Higher Protein Quantity Perceive a Shift from "Poor" to "Good" Sleep: A Randomized Controlled Trial. J Nutr. Dec 10 2020;150(12):3216–3223. doi:10.1093/jn/nxaa302 33096550 | Comparator
483 | Hudson JL, Zhou J, Kim JE, Campbell WW. Incorporating Milk Protein Isolate into an Energy-Restricted Western-Style Eating Pattern Augments Improvements in Blood Pressure and Triglycerides, but Not Body Composition Changes in Adults Classified as Overweight or Obese: A Randomized Controlled Trial. Nutrients. Mar 22 2020;12(3)doi:10.3390/nu12030851 | Comparator
484 | Hudson P, Emmett PM, Taylor CM. Pre-pregnancy maternal BMI classification is associated with preschool childhood diet quality and childhood obesity in the Avon Longitudinal Study of Parents and Children. Public Health Nutr. Dec 2021;24(18):6137–6144. doi: 10.1017/S1368980021001476 33820590 | Intervention or Exposure; Outcome
485 | Hulander E, Lindqvist HM, Wadell AT, Gjertsson I, Winkvist A, Barebring L. Improvements in Body Composition after a Proposed Anti-Inflammatory Diet Are Modified by Employment Status in Weight-Stable Patients with Rheumatoid Arthritis, a Randomized Controlled Crossover Trial. Nutrients. Mar 2 2022;14(5)doi:10.3390/nu14051058 | Health Status; Duration of Intervention
486 | Huls A, Wright MN, Bogl LH, Polygenic risk for obesity and its interaction with lifestyle and sociodemographic factors in European children and adolescents. Int J Obes (Lond). Jun 2021;45(6):1321–1330. doi:10.1038/s41366-021-00795-5 33753884 | Intervention or Exposure
487 | Hunter SR, Considine RV, Mattes RD. Almond consumption decreases android fat mass percentage in adults with high android subcutaneous adiposity but does not change HbA1c in a randomised controlled trial. Br J Nutr. Mar 28 2022;127(6):850–861. doi:10.1017/S0007114521001495 33955348 | Intervention or Exposure; Comparator
488 | Huseinovic E, Hornell A, Johansson I, Esberg A, Lindahl B, Winkvist A. Changes in food intake patterns during 2000–2007 and 20082016 in the population-based Northern Sweden Diet Database. Article. Nutr J. Jul 12 2019;18(1):36. doi: 10.1186/s12937-019-0464-0 31299991 | Study design; Outcome
489 | Hwang J, Shin D, Kim H, Kwon O. Association of maternal dietary patterns during pregnancy with small-for-gestational-age infants: Korean Mothers and Children's Environmental Health (MOCEH) study. Am J Clin Nutr. Feb 9 2022;115(2):471–481. doi: 10.1093/ajcn/nqab340 34625785 | Outcome
490 | Ibe Y, Takahashi Y, Sone H. Food groups and weight gain in Japanese men. Article. Clin Obes. Jun 2014;4(3):157–64. doi: 10.1111/cob.12056 25826771 | Intervention or Exposure
491 | Ibsen DB, Christiansen AH, Olsen A, Adherence to the EAT-Lancet Diet and Risk of Stroke and Stroke Subtypes: A Cohort Study. Article. Stroke. Jan 2022;53(1):154–163. doi:10.1161/STROKEAHA.121.036738 34872335 | Outcome
492 | Imai C, Takimoto H, Fudono A, Application of the Nutrient-Rich Food Index 9.3 and the Dietary Inflammatory Index for Assessing Maternal Dietary Quality in Japan: A Single-Center Birth Cohort Study. Nutrients. Aug 19 2021;13(8)doi: 10.3390/nu13082854 | Study design; Outcome
493 | Imai C, Takimoto H, Kurotani K, Diet Quality and Its Relationship with Weight Characteristics in Pregnant Japanese Women: A Single-Center Birth Cohort Study. Nutrients. Apr 10 2023;15(8)doi:10.3390/nu15081827 | Outcome
494 | Imai T, Miyamoto K, Sezaki A, Traditional Japanese Diet Score - Association with Obesity, Incidence of Ischemic Heart Disease, and Healthy Life Expectancy in a Global Comparative Study. Article. J Nutr Health Aging. Aug 2019;23(8):717–724. doi: 10.1007/s12603-019-1219-5 31560029 | Study design
495 | Innocenti A, Fusi J, Cammisuli DM, Franzoni F, Galetta F, Pruneti C. Effects of Mediterranean diet and weight loss on blood-lipid profile in overweight adults with hypercholesterolemia. Article. Progress in Nutrition. Dec 2019;21(4):889–899. doi:10.23751/pn.v21i4.8089 | Study design
496 | Ishitsuka K, Yamamoto-Hanada K, Mezawa H, Association between pre-pregnancy weight status and dietary patterns during pregnancy: results from the Japan Environment and Children's Study. Public Health Nutr. Sep 2023;26(9):1807–1814. doi: 10.1017/S1368980023000770 37129016 | Study design; Comparator
497 | Itkonen ST, Paivarinta E, Pellinen T, Partial Replacement of Animal Proteins with Plant Proteins for 12 Weeks Accelerates Bone Turnover Among Healthy Adults: A Randomized Clinical Trial. J Nutr. Jan 4 2021;151(1):11–19. doi:10.1093/jn/nxaa264 32939557 | Intervention or Exposure - Foods/Beverages Not Reported
498 | Ivan CR, Messina A, Cibelli G, Italian Ketogenic Mediterranean Diet in Overweight and Obese Patients with Prediabetes or Type 2 Diabetes. Nutrients. Oct 18 2022;14(20)doi:10.3390/nu14204361 | Duration of Intervention; Comparator
499 | Iversen KN, Dicksved J, Zoki C, The Effects of High Fiber Rye, Compared to Refined Wheat, on Gut Microbiota Composition, Plasma Short Chain Fatty Acids, and Implications for Weight Loss and Metabolic Risk Factors (the RyeWeight Study). Nutrients. Apr 17 2022;14(8):N.PAG–N.PAG. doi:10.3390/nu14081669 | Intervention or Exposure - Foods/Beverages Not Reported
500 | Jackson KH, Van Guilder GP, Tintle N, Tate B, McFadden J, Perry CA. Plasma fatty acid responses to a calorie-restricted, DASH-style diet with lean beef. Article. Prostaglandins Leukot Essent Fatty Acids. Apr 2022;179:102413. doi: 10.1016/j.plefa.2022.102413 35395436 | Intervention or Exposure; Outcome
501 | Jain P, Danaei G, Manson JE, Robins JM, Flernan MA. Weight Gain After Smoking Cessation and Lifestyle Strategies to Reduce it. Epidemiology. Jan 2020;31(1):7–14. doi:10.1097/EDE.0000000000001106 31569119 | Intervention or Exposure; Comparator
502 | Jain V, Kumar B, Sharma A, A comprehensive yoga programme for weight reduction in children & adolescents with obesity: A randomized controlled trial. Indian J Med Res. Mar 2022;155(3&4):387–396. doi:10.4103/ijmr.UMR_525_20 36124513 | Intervention or Exposure; Country
503 | Jansen LT, Yang N, Wong JMW, Prolonged Glycemic Adaptation Following Transition From a Low- to High-Carbohydrate Diet A Randomized Controlled Feeding Trial. Article in Press. Diabetes Care. Mar 1 2022;45(3):576–584. doi:10.2337/dc21-1970 35108378 | Duration of Intervention
504 | Janumala I, Toro-Ramos T, Widen E, Increased Visceral Adipose Tissue Without Weight Retention at 59 Weeks Postpartum. Journal Article; Randomized Controlled Trial; Research Support, N.I.H., Extramural. Obesity (Silver Spring). Mar 2020;28(3):552–562. doi: 10.1002/oby.22736 32030911 | Intervention or Exposure
505 | Jardi C, Aparicio E, Bedmar C, Food Consumption during Pregnancy and Post-Partum. ECLIPSES Study. Article. Nutrients. Oct 14 2019;11(10)doi:10.3390/nu11102447 | Outcome
506 | Jayasinghe SN, Breier BH, McNaughton SA, Dietary Patterns in New Zealand Women: Evaluating Differences in Body Composition and Metabolic Biomarkers. Article. Nutrients. Jul 18 2019;11(7)doi:10.3390/nu11071643 | Study design
507 | Jen V, Braun KVE, Karagounis LG, Longitudinal association of dietary protein intake in infancy and adiposity throughout childhood. Article. Clin Nutr. Jun 2019;38(3):1296–1302. doi: 10.1016/j.clnu.2018.05.013 29914777 | Intervention or Exposure
508 | Jeon Y, Limketkai BN. Implications of Dietary Impact on Hepatic Steatosis and IBD. Inflamm Bowel Dis. Jan 1 2021;27(1):10–11. doi: 10.1093/ibd/izaa098 32440694 | Study design; Intervention or Exposure; Outcome; Publication status
509 | Jeruszka-Bielak M, Hamulka J, Czarniecka-Skubina E, Dietary-Physical Activity Patterns in the Health Context of Older Polish Adults: The 'ABC of Healthy Eating' Project. Nutrients. Sep 11 2022;14(18)doi:10.3390/nu14183757 | Study design; Intervention or Exposure
510 | Jeziorek M, Szuba A, Kujawa K, Regulska-llow B. The Effect of a Low-Carbohydrate, High-Fat Diet versus Moderate-Carbohydrate and Fat Diet on Body Composition in Patients with Lipedema. Article. Diabetes Metab Syndr Obes. 2022;15:2545–2561. doi:10.2147/DMSO.S377720 36035515 | Intervention or Exposure - Foods/Beverages Not Reported
511 | Jia J, Levy DE, McCurley JL, Anderson EM, Thorndike AN. Influence of Health Literacy and Numeracy on the Effectiveness of a Behavioral Workplace Intervention to Prevent Weight Gain and Improve Diet: A Subgroup Analysis of the Choosewell 365 Randomized, Controlled Trial. Journal: Conference Abstract. Journal of General Internal Medicine. Jul 2021;36(Suppl 1):S67–S68. | Outcome
512 | Jia Y, Guo D, Sun L, Diet, Lifestyle Behaviours and Other Risk Factors Associated With Type 2 Diabetes Beyond Body Mass Index: A Mendelian Randomization Study. Can J Diabetes. Dec 2022;46(8):822–828. doi: 10.1016/j.jcjd.2022.06.001 35835669 | Publication status
513 | Jiang F, Li Y, Xu P, The efficacy of the Dietary Approaches to Stop Hypertension diet with respect to improving pregnancy outcomes in women with hypertensive disorders. J Hum Nutr Diet. Dec 2019;32(6):713–718. doi: 10.1111/jhn.12654 30941817 | Outcome
514 | Jiang L, Audouze K, Romero Herrera JA, Conflicting associations between dietary patterns and changes of anthropometric traits across subgroups of middle-aged women and men. Clin Nutr. Jan 2020;39(1):265–275. doi:10.1016/j.clnu.2019.02.003 30857909 | Intervention or Exposure
515 | Jianguo L, Yong P, Hanyu L, Effect of microecological preparation combined with an improved low-carbon diet on fat metabolism and intestinal barrier function in obese patients. Article. Chinese Journal of Tissue Engineering Research. 2021;25(29):4672–4679. | Intervention or Exposure - Foods/Beverages Not Reported
516 | Jimenez AM, Oliva SL, Vilar EG, The Mediterranean diet pattern with intermittent semi-fasting may facilitate weight loss: Randomised controlled trial. Article. Mediterranean Journal of Nutrition and Metabolism. 2019;12(2):153–161. | Duration of Intervention
517 | Johansson U, Ohlund I, Lindberg L, A randomized, controlled trial of a Nordic, protein-reduced complementary diet in infants: effects on body composition, growth, biomarkers, and dietary intake at 12 and 18 months. Am J Clin Nutr. Jun 2023;117(6):1219–1231. doi:10.1016/j.ajcnut.2023.03.020 36990225 | Intervention or Exposure
518 | Johansson U, Ohlund I, Lindberg L, Hernell O, Lonnerdal B, Lind T. A randomised, controlled trial of a Nordic, protein-reduced complementary diet: effects on dietary intake, biomarkers and growth until 18 months of age. Journal article; Conference proceeding. Journal of pediatric gastroenterology and nutrition. 2022;74(2):914–915. | Publication status
519 | Johnson KO, Holliday A, Mistry N, An Increase in Fat-Free Mass is Associated with Higher Appetite and Energy Intake in Older Adults: A Randomised Control Trial. Nutrients. Jan 1 2021;13(1)doi:10.3390/nu13010141 | Intervention or Exposure
520 | Jones JM, Schonherr DM, Zaitsoff S, Pullmer R. Changing from the inside out? Examining relationships between overweight identification, dieting behaviours, and body measurements over time. Article. British journal of health psychology. 2019;24(2):460–476.30924253 | Intervention or Exposure
521 | Jones LR, Emmett PM, Hays NP, Shahkhalili Y, Taylor CM. Association of Nutrition in Early Childhood with Body Composition and Leptin in Later Childhood and Early Adulthood. Article. Nutrients. Sep 18 2021;13(9)doi:10.3390/nu13093264 | Intervention or Exposure
522 | Jonsson J, Renault KM, Garcia-Calzon S, Lifestyle Intervention in Pregnant Women With Obesity Impacts Cord Blood DNA Methylation, Which Associates With Body Composition in the Offspring. Article. Diabetes. Apr 2021;70(4):854–866. doi: 10.2337/db20-0487 33431374 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
523 | Jontony N, Hill EB, Taylor CA, Diet Ouality, Carotenoid Status, and Body Composition in NCAA Division I Athletes. Am J Health Behav. Jul 1 2020;44(4):432–443. doi:10.5993/AJHB.44.4.6 32553025 | Intervention or Exposure; Outcome; Comparator
524 | Jospe MR, Roy M, Brown RC, Intermittent fasting, Paleolithic, or Mediterranean diets in the real world: exploratory secondary analyses of a weight-loss trial that included choice of diet and exercise. Am J Clin Nutr. Mar 1 2020;111(3):503–514. doi: 10.1093/ajcn/nqz330 31879752 | Size or Power
525 | Ju Y, Zhang C, Zhang Z, Effect of Dietary Fiber (Oat Bran) Supplement in Heart Rate Lowering in Patients with Hypertension: A Randomized DASH-Diet-Controlled Clinical Trial. Article. Nutrients. Jul 30 2022;14(15)doi:10.3390/nu14153148 | Outcome; Comparator
526 | Jung M, Park S, Kim H, Kwon O. Association of Diet Ouality with Low Muscle Mass-Function in Korean Elderly. Article. Int J Environ Res Public Health. Jul 31 2019;16(15)doi: 10.3390/ijerph16152733 | Study design
527 | Jurado-Fasoli L, De-la OA, Castillo MJ, Amaro-Gahete FJ. Dietary differences between metabolically healthy overweight-obese and metabolically unhealthy overweight-obese adults. Br J Nutr. Nov 28 2019;122(10):1113–1119. doi:10.1017/S0007114519002071 31439053 | Study design
528 | Juraschek SP, Miller ER, 3rd, Chang AR, Anderson CAM, Hall JE, Appel LJ. Effects of Sodium Reduction on Energy, Metabolism, Weight, Thirst, and Urine Volume: Results From the DASH (Dietary Approaches to Stop Hypertension)-Sodium Trial. Hypertension. Mar 2020;75(3):723–729. doi:10.1161/HYPERTENSIONAHA.119.13932 31957521 | Duration of Intervention
529 | Kahleova H, Berrien-Lopez R, Holtz D, Nutrition for Hospital Workers During a Crisis: Effect of a Plant-Based Dietary Intervention on Cardiometabolic Outcomes and Quality of Life in Healthcare Employees During the COVID-19 Pandemic. Am J Lifestyle Med. May-Jun 2022;16(3):399–407. doi:10.1177/15598276211050339 35698577 | Intervention or Exposure - Foods/Beverages Not Reported
530 | Kahleova H, Hlozkova A, Fleeman R, Fletcher K, Holubkov R, Barnard ND. Fat Quantity and Quality, as Part of a Low-Fat, Vegan Diet, Are Associated with Changes in Body Composition, Insulin Resistance, and Insulin Secretion. A 16-Week Randomized Controlled Trial. Journal Article; Randomized Controlled Trial. Nutrients. Mar 13 2019;11(3)doi:10.3390/nu11030615 | Intervention or Exposure - Foods/Beverages Not Reported
531 | Kahleova H, Holubkov R, Barnard N. 506-P: Weight Loss Is Associated with Changes in Gut Microbiome: A Randomized, Crossove Trial Comparing a Mediterranean and a Low-Fat Vegan Diet in Overweight Adults. Diabetes. 2021;70:N.PAG–N.PAG. | Intervention or Exposure - Foods/Beverages Not Reported
532 | Kahleova H, McCann J, Alwarith J, A plant-based diet in overweight adults in a 16-week randomized clinical trial: The role of dietary acid load. Clin Nutr ESPEN. Aug 2021;44:150–158. doi:10.1016/j.clnesp.2021.05.015 34330460 | Intervention or Exposure - Foods/Beverages Not Reported
533 | Kahleova H, Petersen KF, Shulman Gl, A dietary intervention to alter insulin sensitivity, intramyocellular and hepatocellular lipids, postprandial metabolism, and body weight: a 16-week randomised trial. Journal: Conference Abstract. Diabetologia. Sep 2020;63(Suppl 1):S16–S17. | Publication status
534 | Kahleova H, Petersen KF, Shulman Gl, Effect of a Low-Fat Vegan Diet on Body Weight, Insulin Sensitivity, Postprandial Metabolism, and Intramyocellular and Hepatocellular Lipid Levels in Overweight Adults: A Randomized Clinical Trial. JAMA Netw Open. Nov 2 2020;3(11):e2025454. doi:10.1001/jamanetworkopen.2020.25454 33252690 | Intervention or Exposure - Foods/Beverages Not Reported
535 | Kahleova H, Rembert E, Alwarith J, Effects of a Low-Fat Vegan Diet on Gut Microbiota in Overweight Individuals and Relationships with Body Weight, Body Composition, and Insulin Sensitivity. A Randomized Clinical Trial. Nutrients. Sep 24 2020;12(10)doi:10.3390/nu12102917 | Intervention or Exposure - Foods/Beverages Not Reported
536 | Kahleova H, Rembert E, Nowak A, Holubkov R, Barnard ND. Effect of a diet intervention on cardiometabolic outcomes: Does race matter? A randomized clinical trial. Clin Nutr ESPEN. Feb 2021;41:126–128. doi:10.1016/j.clnesp.2020.12.012 33487254 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
537 | Kahleova H, Znayenko-Miller T, Uribarri J, Holubkov R, Barnard ND. Dietary advanced glycation products and their associations with insulin sensitivity and body weight: A 16-week randomized clinical trial. Article in Press. Obes Sci Pract. Jun 2023;9(3):235–242. doi:10.1002/osp4.646 37287522 | Intervention or Exposure
538 | Kalam F, Gabel K, Cienfuegos S, Alternate day fasting combined with a low-carbohydrate diet for weight loss, weight maintenance, and metabolic disease risk reduction. Article. Obes Sci Pract. Dec 2019;5(6):531–539. doi:10.1002/osp4.367 31890243 | Study design; Intervention or Exposure - Foods/Beverages Not Reported; Comparator
539 | Kaliora AC, Gioxari A, Kalafati IP, Diolintzi A, Kokkinos A, Dedoussis GV. The Effectiveness of Mediterranean Diet in Nonalcoholic Fatty Liver Disease Clinical Course: An Intervention Study. Article. J Med Food. Jul 2019;22(7):729–740. doi:10.1089/jmf.2018.0020 31290733 | Study design; Health Status
540 | Kalkuz S, Demircan A. Effects of the Mediterranean diet adherence on body composition, blood parameters and quality of life in adults. Postgrad Med J. Dec 2021;97(1154):798–802. doi:10.1136/postgradmedj-2020-138667 33184134 | Study design
541 | Kamdar N, Hughes SO, Chan W, Power TG, Meininger J. Indirect Effects of Food Insecurity on Body Mass Index Through Feeding Style and Dietary Quality Among Low-Income Hispanic Preschoolers. Article. J Nutr Educ Behav. Jul-Aug 2019;51(7):876–884. doi: 10.1016/j.jneb.2019.02.010 30975581 | Intervention or Exposure; Outcome
542 | Kan J, Ni J, Xue K, Personalized Nutrition Intervention Improves Health Status in Overweight/Obese Chinese Adults: A Randomized Controlled Trial. Front Nutr. 2022;9:919882. doi:10.3389/fnut.2022.919882 35811975 | Intervention or Exposure
543 | Kanellopoulou A, Giannakopoulou SP, Notara V, The association between adherence to the Mediterranean diet and childhood obesity; the role of family structure: Results from an epidemiological study in 1728 Greek students. Nutr Health. Mar 2021;27(1):39–47. doi: 10.1177/0260106020952600 33073650 | Study design
544 | Kanellopoulou A, Kosti Rl, Notara V, Dietary Patterns, Weight Perception and Obesity Status, among 10–12-Year-Old Children; an Epidemiological Study in Greece. Children (Basel). Jul 23 2021;8(8)doi:10.3390/children8080626 | Study design
545 | Kang M, Park SY, Shvetsov YB, Gender differences in sociodemographic and lifestyle factors associated with diet quality in a multiethnic population. Article. Nutrition. 2019;66:147–152.31288218 | Study design; Outcome
546 | Kaplan A, Zelicha H, Yaskolka Meir A, The effect of a high-polyphenol Mediterranean diet (Green-MED) combined with physical activity on age-related brain atrophy: the Dietary Intervention Randomized Controlled Trial Polyphenols Unprocessed Study (DIRECT PLUS). Am J Clin Nutr. May 1 2022;115(5): 1270–1281. doi:10.1093/ajcn/nqac001 35021194 | Comparator
547 | Karampola M, Argiriou A, Hitoglou-Makedou A. Study on dietary constituents, HS-CRP serum levels and investigation of correlation between them in excess weight adolescents. Article. Hippokratia. 2020;23(1):3–8. | Study design; Comparator
548 | Karimbeiki R, Alipoor E, Yaseri M, Shivappa N, Hebert JR, Hosseinzadeh-Attar MJ. Association between the dietary inflammatory index and obesity in otherwise healthy adults: Role of age and sex. Int J Clin Pract. Oct 2021;75(10):e14567. doi:10.1111/ijcp.14567 34165878 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
549 | Karimi T, Eini-Zinab H, Rezazadeh A, Moslemi Z. Maternal dietary diversity and nutritional adequacy in relation with anthropometric measurements of newborns at birth: a cohort study in Tehran city. BMC Pediatr. Mar 12 2022;22(1):129. doi: 10.1186/s12887-021-03102-3 35279127 | Intervention or Exposure; Outcome
550 | Karlsson J, Galavazi M, Jansson S, Jendle J. Effects on body weight, eating behavior, and quality of life of a low-energy diet combined with behavioral group treatment of persons with class II or III obesity: A 2-year pilot study. Article. Obes Sci Pract. Feb 2021;7(1):4–13. doi:10.1002/osp4.464 33680487 | Study design; Intervention or Exposure
551 | Karmali S, Battram DS, Burke SM, Perspectives and Impact of a Parent-Child Intervention on Dietary Intake and Physical Activity Behaviours, Parental Motivation, and Parental Body Composition: A Randomized Controlled Trial. Int J Environ Res Public Health. Sep 18 2020; 17(18)doi: 10.3390/ijerph17186822 | Intervention or Exposure; Comparator
552 | Katsagoni CN, Psarra G, Georgoulis M, High and moderate adherence to Mediterranean lifestyle is inversely associated with overweight, general and abdominal obesity in children and adolescents: The MediLIFE-index. Nutr Res. Jan 2020;73:38–47. doi: 10.1016/j.nutres.2019.09.009 31841746 | Study design
553 | Keenan S, Cooke MB, Chen WS, Wu S, Belski R. The Effects of Intermittent Fasting and Continuous Energy Restriction with Exercise on Cardiometabolic Biomarkers, Dietary Compliance, and Perceived Hunger and Mood: Secondary Outcomes of a Randomised, Controlled Trial. Nutrients. Jul 26 2022;14(15)doi:10.3390/nu14153071 | Intervention or Exposure - Foods/Beverages Not Reported
554 | Kelly R, Hanus A, Payne-Foster P, Calhoun J, Stout R, Sherman BW. Health Benefits of a 16-Week Whole Food, High Fiber, Plant Predominant Diet among U.S. Employees. Article in Press. Am J Health Promot. Feb 2023;37(2):168–176. doi:10.1177/08901171221116066 35852927 | Study design
555 | Kempf K, Rohling M, Banzer W, Early and Strong Leptin Reduction Is Predictive for Long-Term Weight Loss during High-Protein, Low-Glycaemic Meal Replacement-A Subanalysis of the Randomised-Controlled ACOORH Trial. Article. Nutrients. Jun 18 2022;14(12)doi:10.3390/nu14122537 | Intervention or Exposure
556 | Kendel Jovanovic G, Mrakovcic-Sutic I, Pavicic Zezelj S, Metabolic and Hepatic Effects of Energy-Reduced Anti-Inflammatory Diet in Younger Adults with Obesity. Journal Article; Randomized Controlled Trial. Can J Gastroenterol Hepatol. 2021;2021:6649142. doi:10.1155/2021/6649142 33628758 | Intervention or Exposure - Foods/Beverages Not Reported
557 | Kendel Jovanovic G, Mrakovcic-Sutic I, Pavicic Zezelj S, Susa B, Rahelic D, Klobucar Majanovic S. The Efficacy of an Energy-Restricted Anti-Inflammatory Diet for the Management of Obesity in Younger Adults. Nutrients. Nov 22 2020; 12(11)doi:10.3390/nu12113583 | Intervention or Exposure - Foods/Beverages Not Reported
558 | Keogh JB, Pedersen E, Petersen KS, Clifton PM. Effects of intermittent compared to continuous energy restriction on short-term weight loss and long-term weight loss maintenance. Article. Clin Obes. Jun 2014;4(3):150–6. doi:10.1111/cob.12052 25826770 | Intervention or Exposure
559 | Kerr JA, Liu RS, Gasser CE, Diet quality trajectories and cardiovascular phenotypes/metabolic syndrome risk by 11–12 years. Int J Obes (Lond). Jul 2021;45(7):1392–1403. doi:10.1038/s41366-021-00800-x 33824404 | Outcome
560 | Kesary Y, Avital K, Hiersch L. Maternal plant-based diet during gestation and pregnancy outcomes. Arch Gynecol Obstet. Oct 2020;302(4):887–898. doi:10.1007/s00404-020-05689-x 32776295 | Study design
561 | Keshavarz P, Lane G, Pahwa P, Dietary Patterns of Off-Reserve Indigenous Peoples in Canada and Their Association with Chronic Conditions. Nutrients. Mar 20 2023;15(6)doi:10.3390/nu15061485 | Study design
562 | Khalatbari-Soltani S, Marques-Vidal P, Imamura F, Forouhi NG. Prospective association between adherence to the Mediterranean diet and hepatic steatosis: the Swiss CoLaus cohort study. BMJ Open. Dec 22 2020;10(12):e040959. doi: 10.1136/bmjopen-2020-040959 | Outcome
563 | Khaled K, Hundley V, Almilaji O, Koeppen M, Tsofliou F. A Priori and a Posteriori Dietary Patterns in Women of Childbearing Age in the UK. Nutrients. Sep 24 2020;12(10)doi:10.3390/nu12102921 | Study design
564 | Khalfallah M, Elnagar B, Soliman SS, Eissa A, Allaithy A. The Value of Intermittent Fasting and Low Carbohydrate Diet in Prediabetic Patients for the Prevention of Cardiovascular Diseases. Article in Press. Arq Bras Cardiol. 2023;120(4):e20220606. Papel do Jejum Intermitente e da Dieta Restrita em Carboidratos na Prevencao de Doencas Cardiovasculares em Pacientes Pre-Diabeticos. doi: 10.36660/abc.20220606 37042857 | Intervention or Exposure - Foods/Beverages Not Reported
565 | Khalili H, Hakansson N, Chan SS, Adherence to a Mediterranean diet is associated with a lower risk of later-onset Crohn's disease: results from two large prospective cohort studies. Gut. Sep 2020;69(9):1637–1644. doi: 10.1136/gutjnl-2019-319505 | Outcome
566 | Khan I, Kwon M, Shivappa N, J RH, Kim MK. Proinflammatory Dietary Intake is Associated with Increased Risk of Metabolic Syndrome and Its Components: Results from the Population-Based Prospective Study. Article. Nutrients. Apr 24 2020;12(4)doi:10.3390/nu12041196 | Intervention or Exposure - Foods/Beverages Not Reported
567 | Khanal P, He L, Degens H, Dietary Protein Requirement Threshold and Micronutrients Profile in Healthy Older Women Based on Relative Skeletal Muscle Mass. Nutrients. Sep 1 2021;13(9)doi:10.3390/nu13093076 | Study design; Intervention or Exposure
568 | Kharmats AY, Popp C, Hu L, A randomized clinical trial comparing low-fat with precision nutrition-based diets for weight loss: impact on glycemic variability and HbA1c. Am J Clin Nutr. Aug 2023;118(2):443–451. doi:10.1016/j.ajcnut.2023.05.026 37236549 | Intervention or Exposure
569 | Khazrai Y, Di Rosa C, Lattanzi G, Effectiveness of a very low calorie ketogenic diet with meal replacements on body weight and composition. Journal: Conference Abstract. Obesity reviews. 2020;21(SUPPL 1) | Publication status
570 | Khoury J, Henriksen T, Christophersen B, Tonstad S. Effect of a cholesterol-lowering diet on maternal, cord, and neonatal lipids, and pregnancy outcome: a randomized clinical trial. Am J Obstet Gynecol. Oct 2005;193(4):1292–301. doi:10.1016/j.ajog.2005.05.016 16202717 | Outcome
571 | Killeen SL, Phillips CM, Delahunt A, Effect of an Antenatal Lifestyle Intervention on Dietary Inflammatory Index and Its Associations with Maternal and Fetal Outcomes: A Secondary Analysis of the PEARS Trial. Nutrients. Aug 15 2021;13(8)doi: 10.3390/nu13082798 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
572 | Kim HJ, Tak YJ, Lee SY, Seo JP. Effects of a 12-Week Diet versus Diet plus Aerobic and Resistance Exercise Program on Acylated and Desacylated Ghrelin, and Ghrelin O-Acyltransferase in Adolescent Girls with Obesity. Article. Int J Environ Res Public Health. Jan 28 2022;19(3)doi:10.3390/ijerph19031480 | Intervention or Exposure; Comparator
573 | Kim HS, Jung SJ, Mun EG, Kim MS, Cho SM, Cha YS. Effects of a Rice-Based Diet in Korean Adolescents Who Habitually Skip Breakfast: A Randomized, Parallel Group Clinical Trial. Nutrients. Mar 5 2021;13(3)doi:10.3390/nu13030853 | Intervention or Exposure - Foods/Beverages Not Reported
574 | Kim J, Giovannucci E. Healthful Plant-Based Diet and Incidence of Type 2 Diabetes in Asian Population. Article. Nutrients. Jul 27 2022;14(15)doi:10.3390/nu14153078 | Outcome
575 | Kim J, Kim M, Shin Y, Cho JH, Lee D, Kim Y. Association between Dietary Diversity Score and Metabolic Syndrome in Korean Adults: A Community-Based Prospective Cohort Study. Nutrients. Dec 13 2022;14(24)doi: 10.3390/nu14245298 | Intervention or Exposure
576 | Kim J, Lee Y, Won CW, Dietary Patterns and Frailty in Older Korean Adults: Results from the Korean Frailty and Aging Cohort Study. Article. Nutrients. Feb 12 2021;13(2):1–10. doi:10.3390/nu13020601 | Size or Power
577 | Kim MJ, Hur HJ, Jang DJ, Kim MS, Park S, Yang HJ. Inverse association of a traditional Korean diet composed of a multigrain rice-containing meal with fruits and nuts with metabolic syndrome risk: The KoGES. Front Nutr. 2022;9:1051637. doi: 10.3389/fnut.2022.1051637 36438748 | Study design
578 | Kim MJ, Lim HS, Lee HH, Kim TH, Park Y. Dietary assessment, nutrition knowledge, and pregnancy outcome in high-risk pregnant Korean women. Article. Clinical and Experimental Obstetrics & Gynecology. Oct 15 2021;48(5):1178–1185. doi:10.31083/j.ceog4805188 | Outcome
579 | Kim Y, Kim YM, Shin MH, Koh SB, Chang Kim H, Kim MK. Empirically identified dietary patterns and metabolic syndrome risk in a prospective cohort study: The Cardiovascular Disease Association Study. Article. Clin Nutr. Oct 2022;41(10):2156–2162. doi:10.1016/j.clnu.2022.07.038 36067587 | Outcome
580 | Kim Y, Lu S, Ho JE, Proteins as Mediators of the Association Between Diet Ouality and Incident Cardiovascular Disease and All-Cause Mortality: The Framingham Heart Study. Article. J Am Heart Assoc. Sep 21 2021;10(18):e021245. doi: 10.1161/JAHA.121.021245 34482708 | Outcome
581 | Klonizakis M, Grammatikopoulou MG, Theodoridis X, Milner M, Liu Y, Chourdakis M. Effects of Long-Versus Short-Term Exposure to the Mediterranean Diet on Skin Microvascular Function and Ouality of Life of Healthy Adults in Greece and the UK. Article. Nutrients. Oct 16 2019;11(10)doi:10.3390/nu11102487 | Study design; Duration of Intervention; Outcome
582 | Knight R, Cedillo Y, Judd S, Tison S, Baker E, Moellering D. Dietary inflammation score is associated with perceived stress, depression, and cardiometabolic health risk factors among a young adult cohort of women. Article in Press. Clin Nutr ESPEN. Oct 2022;51:470–477. doi:10.1016/j.clnesp.2022.06.013 36184244 | Study design
583 | Kocaadam-Bozkurt B, Bozkurt O. Relationship between adherence to the Mediterranean diet, sustainable and healthy eating behaviors, and awareness of reducing the ecological footprint. Int J Environ Health Res. Apr 2023;33(4):430–440. doi: 10.1080/09603123.2023.2172384 36726049 | Study design
584 | Kocaadam-Bozkurt B, Karacil Ermumcu MS, Erdogan Govez N, Association between adherence to the Mediterranean diet with anthropometric measurements and nutritional status in adolescents. Nutr Hosp. Apr 20 2023;40(2):368–376. Asociacion entre la adherencia a la dieta mediterranea y las medidas antropometricas y el estado nutricional en adolescentes. doi: 10.20960/nh.04545 36880734 | Study design
585 | Kocaadam-Bozkurt B, Sozlu S, Macit-Celebi MS. Exploring the understanding of how parenting influences the children's nutritional status, physical activity, and BMI. Front Nutr. Jan 11 2022;9:1096182. doi:10.3389/fnut.2022.1096182 36712500 | Study design; Intervention or Exposure
586 | Koeder C, Alzughayyar D, Anand C, The healthful plant-based diet index as a tool for obesity prevention-The healthy lifestyle community program cohort 3 study. Article in Press. Obes Sci Pract. Jun 2023;9(3):296–304. doi:10.1002/osp4.649 37287519 | Size or Power
587 | Koeder C, Kranz RM, Anand C, Effect of a 1-Year Controlled Lifestyle Intervention on Body Weight and Other Risk Markers (the Healthy Lifestyle Community Programme, Cohort 2). Obes Facts. 2022;15(2):228–239. doi: 10.1159/000521164 34923493 | Intervention or Exposure; Comparator
588 | Koeryaman MT, Pallikadavath S, Ryder IH, Kandala N. The Effectiveness of a Web-Based Application for a Balanced Diet and Healthy Weight Among Indonesian Pregnant Women: Randomized Controlled Trial. JMIR Form Res. Jan 30 2023;7:e38378. doi: 10.2196/38378 36716078 | Intervention or Exposure; Outcome
589 | Kohl J, Brame J, Hauff P, Effects of a Web-Based Weight Loss Program on the Healthy Eating Index-NVS in Adults with Overweight or Obesity and the Association with Dietary, Anthropometric and Cardiometabolic Variables: A Randomized Controlled Clinical Trial. Nutrients. Dec 20 2022;15(1)doi:10.3390/nu15010007 | Size or Power
590 | Kohli A, Pandey RM, Siddhu A, Reddy KS. Development of a diet pattern assessment tool for coronary heart disease risk reduction. Public Health Pract (Oxf). Dec 2022;4:100317. doi: 10.1016/j.puhip.2022.100317 36193539 | Study design
591 | Kominiarek MA, Cordero C, Stuebe AM, Pre-pregnancy Health Behaviors and Gestational Weight Gain Among Hispanic/Latino Women: Hispanic Community Health Study/Study of Latinos. Article in Press. Matern Child Health J. Dec 2021;25(12):2002–2013. doi: 10.1007/s10995-021-03252-x 34647266 | Life stage
592 | Kong NW, Ning H, Zhong VW, Association between diet quality and incident cardiovascular disease stratified by body mass index. Am J Prev Cardiol. Dec 2021;8:100298. doi:10.1016/j.ajpc.2021.100298 34888539 | Outcome
593 | Konieczna J, Fiol M, Colom A, Does Consumption of Ultra-Processed Foods Matter for Liver Health? Prospective Analysis among Older Adults with Metabolic Syndrome. Nutrients. Oct 5 2022;14(19)doi:10.3390/nu14194142 | Outcome
594 | Konieczna J, Romaguera D, Pereira V, Longitudinal association of changes in diet with changes in body weight and waist circumference in subjects at high cardiovascular risk: the PREDIMED trial. Int J Behav Nutr Phys Act. Dec 27 2019;16(1): 139. doi: 10.1186/s12966-019-0893-3 31882021 | Intervention or Exposure
595 | Konieczna J, Yanez A, Monino M, Longitudinal changes in Mediterranean diet and transition between different obesity phenotypes. Clin Nutr. Mar 2020;39(3):966–975. doi:10.1016/j.clnu.2019.04.002 31053509 | Outcome
596 | Konikowska K, Bombala W, Szuba A, Rozanska D, Regulska-llow B. Metabolic Syndrome Is Associated with Low Diet Quality Assessed by the Healthy Eating Index-2015 (HEI-2015) and Low Concentrations of High-Density Lipoprotein Cholesterol. Biomedicines. Oct 5 2022;10(10)doi:10.3390/biomedicines10102487 | Study design
597 | Koo HC, Poh BK, Talib RA. The GReat-Child Trial(TM): A Quasi-Experimental Dietary Intervention among Overweight and Obese Children. Nutrients. Sep 29 2020;12(10)doi:10.3390/nu12102972 | Intervention or Exposure
598 | Kostecka M, Bojanowska M, Kostecka J, Ciolek A. An analysis of dietary patterns and body composition parameters in the Polish population. Rocz PanstwZakl Hig. 2021;72(1):55–66. doi:10.32394/rpzh.2021.0152 | Study design
599 | Kostecka M, Kostecka-Jarecka J, llowiecka K, Kostecka J. An Evaluation of Nutritional Status and Problems with Dietary Compliance in Polish Patients with Celiac Disease. Article. Nutrients. Jun 22 2022;14(13)doi:10.3390/nu14132581 | Intervention or Exposure
600 | Kracht CL, Champagne CM, Hsia DS, Association Between Meeting Physical Activity, Sleep, and Dietary Guidelines and Cardiometabolic Risk Factors and Adiposity in Adolescents. J Adolesc Health. Jun 2020;66(6):733–739. doi: 10.1016/j.jadohealth.2019.12.011 31987725 | Study design
601 | Krishnan S, Adams SH, Witbracht MG, Weight Loss, but Not Dairy Composition of Diet, Moderately Affects Satiety and Postprandial Gut Hormone Patterns in Adults. J Nutr. Jan 4 2021;151(1):245–254. doi:10.1093/jn/nxaa327 33245130 | Intervention or Exposure - Foods/Beverages Not Reported
602 | Kruse M, Hornemann S, Ost AC, An Isocaloric High-Fat Diet Regulates Partially Genetically Determined Fatty Acid and Carbohydrate Uptake and Metabolism in Subcutaneous Adipose Tissue of Lean Adult Twins. Nutrients. May 16 2023;15(10)doi:10.3390/nu15102338 | Duration of Intervention
603 | Kuckuck S, van der Valk ES, Scheurink AJW, Levels of hormones regulating appetite and energy homeostasis in response to a 1.5-Year combined lifestyle intervention for obesity. Front Physiol. 2023;14:1010858. doi: 10.3389/fphys.2023.1010858 36891140 | Intervention or Exposure
604 | Kuczmarski MF, Brewer BC, Rawal R, Pohlig RT, Zonderman AB, Evans MK. Aspects of dietary diversity differ in their association with atherosclerotic cardiovascular risk in a racially diverse us adult population. Article. Nutrients. 2019;11(5) | Intervention or Exposure; Outcome
605 | Kunaratnam K, Halaki M, Wen LM, Baur LA, Flood VM. Tracking Preschoolers' Lifestyle Behaviors and Testing Maternal Sociodemographics and BMI in Predicting Child Obesity Risk. Article. J Nutr. Dec 10 2020;150(12):3068–3074. doi: 10.1093/jn/nxaa292 33096560 | Intervention or Exposure
606 | Kunath J, Gunther J, Rauh K, Effects of a lifestyle intervention during pregnancy to prevent excessive gestational weight gain in routine care - the cluster-randomised GeliS trial. Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. BMC Med. Jan 14 2019;17(1):5. doi:10.1186/s12916-018-1235-z 30636636 | Intervention or Exposure; Data overlap
607 | Kwasniewska M, Pikala M, Grygorczuk O, Dietary Antioxidants, Quality of Nutrition and Cardiovascular Characteristics among Omnivores, Flexitarians and Vegetarians in Poland-The Results of Multicenter National Representative Survey WOBASZ. Antioxidants (Basel). Jan 18 2023;12(2)doi:10.3390/antiox12020222 | Study design
608 | Kwiatkowska I, Olszak J, Brozek A, Is It Feasible to Predict Cardiovascular Risk among Healthy Vegans, Lacto-/Ovo-Vegetarians, Pescatarians, and Omnivores under Forty? Article. Int J Environ Res Public Health. Jan 27 2023;20(3)doi:10.3390/ijerph20032237 | Study design
609 | Kwiatkowska I, Olszak J, Formanowicz P, Formanowicz D. Nutritional Status and Habits among People on Vegan, Lacto/Ovo-Vegetarian, Pescatarian and Traditional Diets. Nutrients. Nov 1 2022;14(21)doi:10.3390/nu14214591 | Study design; Intervention or Exposure - Foods/Beverages Not Reported; Outcome
610 | Lafreniere J, Carbonneau E, Laramee C, Is the Canadian healthy eating index 2007 an appropriate diet indicator of metabolic health? insights from dietary pattern analysis in the PREDISE study. Article. Nutrients. 2019;11(7) | Study design
611 | Lai JS, Colega MT, Godfrey KM, Changes in Diet Quality from Pregnancy to 6 Years Postpregnancy and Associations with Cardiometabolic Risk Markers. Nutrients. Apr 13 2023;15(8)doi:10.3390/nu15081870 | Size or Power
612 | Lai JS, Soh SE, Loy SL, Macronutrient composition and food groups associated with gestational weight gain: the GUSTO study. Article. Eur J Nutr. Apr 2019;58(3):1081–1094. doi:10.1007/S00394-018-1623-3 29441408 | Intervention or Exposure; Data overlap
613 | Lai KZH, Semnani-Azad Z, Retnakaran R, Harris SB, Hanley AJ. Changes in adiposity mediate the associations of diet quality with insulin sensitivity and beta-cell function. Nutr Metab Cardiovasc Dis. Oct 28 2021;31(11):3054–3063. doi:10.1016/j.numecd.2021.07.025 34518089 | Size or Power
614 | Lampignano L, Donghia R, Sila A, Mediterranean Diet and Fatty Liver Risk in a Population of Overweight Older Italians: A Propensity Score-Matched Case-Cohort Study. Article. Nutrients. Jan 7 2022;14(2)doi:10.3390/nu14020258 | Outcome
615 | Lampropoulou M, Chaini M, Rigopoulos N, Evangeliou A, Papadopoulou-Legbelou K, Koutelidakis AE. Association Between Serum Lipid Levels in Greek Children with Dyslipidemia and Mediterranean Diet Adherence, Dietary Habits, Lifestyle and Family Socioeconomic Factors. Nutrients. May 29 2020;12(6):1600. doi:10.3390/nu12061600 32485939 | Study design; Outcome; Comparator
616 | Laouali N, Shah S, MacDonald CJ, BMI in the Associations of Plant-Based Diets with Type 2 Diabetes and Hypertension Risks in Women: The E3N Prospective Cohort Study. Article. J Nutr. Sep 4 2021;151(9):2731–2740. doi:10.1093/jn/nxab158 34236437 | Health Status- 100% Diabetes; Outcome
617 | LaRose JG, Neiberg RH, Evans EW, Dietary outcomes within the study of novel approaches to weight gain prevention (SNAP) randomized controlled trial. Journal Article; Randomized Controlled Trial; Research Support, N.I.H., Extramural. Int J Behav Nutr Phys Act. Jan 31 2019;16(1):14. doi:10.1186/s12966-019-0771-z 30704533 | Intervention or Exposure
618 | Larruy-Garcia A, Flores K, Vazquez-Cobela R, Changes in body composition after one year of lifestyle intervention in children at risk of obesity: Preliminary results. Melipop study. Journal article; Conference proceeding. Annals of Nutrition and Metabolism. Sep 2022;78(Suppl 3): 13–13. | Publication status
619 | Laskou F, Bevilacqua G, Westbury LD, A study of diet in older community-dwelling adults in the UK during the COVID-19 pandemic: Findings from the Southampton Longitudinal Study of Ageing (SaLSA). Front Nutr. 2022;9:988575. doi: 10.3389/fnut.2022.988575 36712533 | Intervention or Exposure; Outcome
620 | Latorre-Millan M, Ruperez Al, Gonzalez-Gil EM, Dietary Patterns and Their Association with Body Composition and Cardiometabolic Markers in Children and Adolescents: Genobox Cohort. Nutrients. Nov 8 2020;12(11)doi:10.3390/nu12113424 | Study design
621 | Lavie M, Lavie I, Maslovitz S. Paleolithic diet during pregnancy-A potential beneficial effect on metabolic indices and birth weight. Eur J Obstet Gynecol Reprod Biol. Nov 2019;242:7–11. doi:10.1016/j.ejogrb.2019.08.013 31522093 | Study design
622 | Lavikainen P, Mattila E, Absetz P, Digitally Supported Lifestyle Intervention to Prevent Type 2 Diabetes Through Healthy Habits: Secondary Analysis of Long-Term User Engagement Trajectories in a Randomized Controlled Trial. J Med Internet Res. Feb 24 2022;24(2):e31530. doi:10.2196/31530 | Intervention or Exposure
623 | Lawrence RL, Wall CR, Bloomfield FH. Dietary Patterns and Dietary Adaptations in Women with and without Gestational Diabetes: Evidence from the Growing Up in New Zealand Study. Article. Nutrients. Jan 15 2020;12(1)doi:10.3390/nu12010227 | Outcome; Comparator
624 | Lazarova SV, Jessri M. Associations between dietary patterns and cardiovascular disease risk in Canadian adults: a comparison of partial least squares, reduced rank regression, and the simplified dietary pattern technique. Am J Clin Nutr. Aug 4 2022;116(2):362–377. doi:10.1093/ajcn/nqac117 35511218 | Study design
625 | Lebrun A, Plante AS, Savard C, Tracking of Dietary Intake and Diet Quality from Late Pregnancy to the Postpartum Period. Article. Nutrients. Sep 3 2019;11(9)doi:10.3390/nu11092080 | Intervention or Exposure; Comparator
626 | Lecorguille M, Lioret S, de Lauzon-Guillain B, Association between Dietary Intake of One-Carbon Metabolism Nutrients in the Year before Pregnancy and Birth Anthropometry. Nutrients. Mar 20 2020;12(3)doi:10.3390/nu12030838 | Outcome
627 | Lecorguille M, Schipper M, O'Donnell A, Parental lifestyle patterns around pregnancy and risk of childhood obesity in four European birth cohort studies. Lancet Glob Health. Mar 2023;11 Suppl 1:S5. doi:10.1016/S2214-109X(23)00090-6 36866482 | Publication status
628 | LeCroy MN, Nicastro HL, Truesdale KP, Dietary patterns and associations with BMI in low-income, ethnic minority youth in the USA according to baseline data from four randomised controlled trials. Br J Nutr. Jul 14 2021;126(1):81–91. doi: 10.1017/S0007114520003852 32993818 | Study design
629 | LeCroy MN, Truesdale KP, Matheson DM, Snacking characteristics and patterns and their associations with diet quality and BMI in the Childhood Obesity Prevention and Treatment Research Consortium. Public Health Nutr. Dec 2019;22(17):3189–3199. doi: 10.1017/S1368980019000958 31112114 | Study design; Intervention or Exposure
630 | Lee CY, Robertson MC, Johnston H, Feasibility and Effectiveness of a Worksite-Weight-Loss Program for Cancer Prevention among School-District Employees with Overweight and Obesity. Int J Environ Res Public Health. Dec 29 2022;20(1)doi:10.3390/ijerph20010538 | Intervention or Exposure
631 | Lee CY. A Combination of Glucagon-Like Peptide-1 Receptor Agonist and Dietary Intervention Could Be a Promising Approach for Obesity Treatment. Article. Front Endocrinol (Lausanne). 2021;12:748477. doi:10.3389/fendo.2021.748477 34616367 | Study design
632 | Lee M, Lee Y, Kang I, Shin J, Sorn SR. RMR-Related MAP2K6 Gene Variation on the Risk of Overweight/Obesity in Children: A 3-Year Panel Study. J Pers Med. Feb 2 2021;11(2)doi:10.3390/jpm11020091 | Intervention or Exposure
633 | Lee YQ, Colega M, Sugianto R, Tracking of dietary patterns between pregnancy and 6 years post-pregnancy in a multiethnic Asian cohort: the Growing Up in Singapore Towards healthy Outcomes (GUSTO) study. Article. Eur J Nutr. Mar 2022;61(2):985–1001. doi: 10.1007/s00394-021-02703-z 34686887 | Intervention or Exposure; Outcome
634 | Lee YQ, Lumbers ER, Schumacher TL, Maternal Diet Influences Fetal Growth but Not Fetal Kidney Volume in an Australian Indigenous Pregnancy Cohort. Nutrients. Feb 9 2021;13(2)doi:10.3390/nu13020569 | Outcome
635 | Leite BF, Morimoto MA, Gomes CMF, Dietetic intervention in psoriatic arthritis: the DIETA trial. Adv Rheumatol. Apr 6 2022;62(1):12. doi: 10.1186/s42358-022-00243-6 35387686 | Health Status; Comparator
636 | Leng J, Lui F, Narang B, A Pilot Group-Based Lifestyle Intervention to Promote Weight Loss Among Mexican Immigrants. J Community Health. Dec 2022;47(6):885–893. doi: 10.1007/s10900-022-01124-1 35902442 | Study design; Comparator
637 | Lennerz BS, Mey JT, Henn OH, Ludwig DS. Behavioral Characteristics and Self-Reported Health Status among 2029 Adults Consuming a "Carnivore Diet". Curr Dev Nutr. Dec 2021;5(12):nzab133. doi:10.1093/cdn/nzab133 34934897 | Study design
638 | Lent MR, Atwood M, Bennett WL, Night eating, weight, and health behaviors in adults participating in the Daily24 study. Eat Behav. Apr 2022;45:101605. doi:10.1016/j.eatbeh.2022.101605 35219937 | Study design; Intervention or Exposure
639 | Leszczak J, Czenczek-Lewandowska E, Przysada G, Diet after Stroke and Its Impact on the Components of Body Mass and Functional Fitness-A 4-Month Observation. Article. Nutrients. May 29 2019;11(6)doi:10.3390/nu11061227 | Health Status- 100% CVD
640 | Li B, Pallan M, Liu WJ, The CHIRPY DRAGON intervention in preventing obesity in Chinese primary-school--aged children: A cluster-randomised controlled trial. PLoS Med. Nov 2019;16(11):e1002971. doi:10.1371/journal.pmed.1002971 31770371 | Intervention or Exposure
641 | Li H, Li D, Wang X, The Role of Dietary Patterns and Dietary Quality on Body Composition of Adolescents in Chinese College. Nutrients. Oct 28 2022;14(21)doi:10.3390/nu14214544 | Study design
642 | Li J, Guasch-Ferre M, Chung W, The Mediterranean diet, plasma metabolome, and cardiovascular disease risk. Journal: Article in Press. Eur Heart J. Jul 21 2020;41(28):2645–2656. doi:10.1093/eurheartj/ehaa209 32406924 | Outcome
643 | Li L, Alonso A, Romaguera D, Effect of an Intensive Lifestyle Intervention on Circulating Biomarkers of Atrial Fibrillation-Related Pathways among Adults with Metabolic Syndrome: Results from a Randomized Trial. J Clin Med. Apr 7 2024;13(7)doi:10.3390/jcm13072132 | Outcome
644 | Li M, Shi J, Luo J, Diet Quality among Women with Previous Gestational Diabetes Mellitus in Rural Areas of Hunan Province. Int J Environ Res Public Health. Aug 16 2020;17(16)doi: 10.3390/ijerph17165942 | Study design
645 | Li X, Perelman D, Leong AK, Fragiadakis G, Gardner CD, Snyder MP. Distinct factors associated with short-term and long-term weight loss induced by low-fat or low-carbohydrate diet intervention. Cell Rep Med. Dec 20 2022;3(12):100870. doi: 10.1016/j.xcrm.2022.100870 36516846 | Intervention or Exposure - Foods/Beverages Not Reported
646 | Li X, Zhou T, Ma H, Genetic variation in lean body mass, changes of appetite and weight loss in response to diet interventions: The POUNDS Lost trial. Diabetes Obes Metab. Dec 2020;22(12):2305–2315. doi:10.1111/dom.14155 32734691 | Intervention or Exposure
647 | Liang F, Fu J, Turner-McGrievy G, Association of Body Mass Index and Plant-Based Diet with Cognitive Impairment among Older Chinese Adults: A Prospective, Nationwide Cohort Study. Nutrients. Jul 29 2022;14(15)doi:10.3390/nu14153132 | Outcome
648 | Lichert F. Consumption of whole-grain wheat stabilizes hepatic fat level. Journal: Short Survey. Aktuelle ernahrungsmedizin. 2019;44(2):82–83. | Publication status; Language
649 | Liedes H, Mattila E, Honka A, Associations Between Engagement with the BitHabit Digital Lifestyle Intervention and Changes in Type 2 Diabetes Risk Factors. Stud Health Technol Inform. May 18 2023;302:1009–1010. doi:10.3233/SHTI230328 37203555 | Intervention or Exposure; Publication status
650 | Likhitweerawong N, Boonchooduang N, Kittisakmontri K, Chonchaiya W, Louthrenoo O. Effectiveness of mobile application on changing weight, healthy eating habits, and quality of life in children and adolescents with obesity: a randomized controlled trial. BMC Pediatr. Nov 10 2021;21(1):499. doi:10.1186/s12887-021-02980-x 34758761 | Intervention or Exposure
651 | Lim JH, Kim YS, Lee JE, Dietary pattern and its association with right-colonic diverticulosis. J Gastroenterol Hepatol. Jan 2021;36(1):144–150. doi:10.1111/jgh.15145 32525584 | Outcome
652 | Lim SX, Cox V, Rodrigues N, Evaluation of Preconception Dietary Patterns in Women Enrolled in a Multisite Study. Article. Curr Dev Nutr. Jul 2022;6(7):nzac106. doi:10.1093/cdn/nzac106 36628060 | Study design
653 | Lin D, Chen DD, Huang J, Li Y, Wen XS, Shi HJ. Longitudinal association between the timing of adiposity peak and rebound and overweight at seven years of age. BMC Pediatr. Apr 19 2022;22(1):215. doi: 10.1186/s12887-022-03190-9 35439975 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
654 | Lin YC, Chu CH, Chen YJ, Chen RB, Huang CC. Gestational Age-Related Associations between Early-Life Feeding Trajectories and Growth Outcomes at Term Equivalent Age in Very Preterm Infants. Article. Nutrients. Feb 28 2022;14(5)doi:10.3390/nu14051032 | Intervention or Exposure; Outcome
655 | Lindsay KL, Buss C, Wadhwa PD, Entringer S. The Effect of a Maternal Mediterranean Diet in Pregnancy on Insulin Resistance is Moderated by Maternal Negative Affect. Article. Nutrients. Feb 6 2020;12(2)doi:10.3390/nu12020420 | Outcome
656 | Lindsay KL, Milone GF, Grobman WA, Periconceptional diet quality is associated with gestational diabetes risk and glucose concentrations among nulliparous gravidas. Front Endocrinol (Lausanne). Sep 5 2022;13:940870. doi:10.3389/fendo.2022.940870 36133312 | Outcome
657 | Lindsay KL, Most J, Buehler K, Kebbe M, Altazan AD, Redman LM. Maternal mindful eating as a target for improving metabolic outcomes in pregnant women with obesity. Front Biosci (Landmark Ed). Dec 30 2021;26(12):1548–1558. doi: 10.52586/5048 34994169 | Intervention or Exposure - Foods/Beverages Not Reported
658 | Lisso F, Massari M, Gentilucci M, Longitudinal Nutritional Intakes in Italian Pregnant Women in Comparison with National Nutritional Guidelines. Article. Nutrients. May 5 2022;14(9)doi:10.3390/nu14091944 | Intervention or Exposure; Outcome; Comparator
659 | Litt JS, Alaimo K, Harrall KK, Effects of a community gardening intervention on diet, physical activity, and anthropometry outcomes in the USA (CAPS): an observer-blind, randomised controlled trial. Lancet Planet Health. Jan 2023;7(1):e23–e32. doi: 10.1016/S2542-5196(22)00303-5 36608945 | Intervention or Exposure
660 | Little RB, Murillo AL, Van Der Pol WJ, Diet Quality and the Gut Microbiota in Women Living in Alabama. Am J Prev Med. Jul 2022;63(1 Suppl 1):S37–S46. doi:10.1016/j.amepre.2022.02.015 35725139 | Study design
661 | Liu M, Chen QT, Li ZC, Zhang J, Wang PG, He QQ. Association Between Diet Quality and Cardiometabolic Risk Factor Clustering Stratified by Socioeconomic Status Among Chinese Children. J Acad Nutr Diet. Oct 2021;121(10):1975–1983 e2. doi:10.1016/j.jand.2021.03.009 33893062 | Country
662 | Liu M, Xu J, Li Y, A Town-Level Comprehensive Intervention Study to Reduce Salt Intake in China: Cluster Randomized Controlled Trial. Article. Nutrients. Nov 7 2022;14(21)doi:10.3390/nu14214698 | Intervention or Exposure
663 | Liu Q, Wen Q, Lv J, The Prospective Associations of Lipid Metabolism-Related Dietary Patterns with the Risk of Diabetes in Chinese Adults. Article. Nutrients. Feb 25 2022;14(5)doi:10.3390/nu14050980 | Country
664 | Liu ST, Lin CC, Wei JC. Mediterranean Diet or Mindfulness-Based Stress Reduction and Prevention of Small-for-Gestational-Age Birth Weights in Newborns. JAMA. Apr 5 2022;327(13):1292–1293. doi:10.1001/jama.2022.2164 | Publication status
665 | Liu Y, Sun P, Shuai P, Qiao Q, Li T. Fat-restricted low-glycemic index diet controls weight and improves blood lipid profile: A pilot study among overweight and obese adults in Southwest China. Medicine (Baltimore). May 28 2021;100(21):e26107. doi: 10.1097/MD.0000000000026107 34032752 | Study design; Comparator
666 | Liu YH, Lu LP, Yi MH, Study on the correlation between homocysteine-related dietary patterns and gestational diabetes mellitus:a reduced-rank regression analysis study. Article. BMC Pregnancy Childbirth. Apr 10 2022;22(1):306. doi: 10.1186/s12884-022-04656-5 35399065 | Study design
667 | Liu Z, Gao P, Gao AY, Effectiveness of a Multifaceted Intervention for Prevention of Obesity in Primary School Children in China: A Cluster Randomized Clinical Trial. JAMA Pediatr. Jan 1 2022;176(1):e214375. doi:10.1001/jamapediatrics.2021.4375 34747972 | Intervention or Exposure
668 | Lockard B, Mardock M, Oliver JM, Comparison of Two Diet and Exercise Approaches on Weight Loss and Health Outcomes in Obese Women. Int J Environ Res Public Health. Apr 17 2022;19(8)doi:10.3390/ijerph19084877 | Intervention or Exposure; Duration of Intervention
669 | Longo UG, Sofi F, Dinu M, Alpine junior world ski championship: nutritional habits and performance in elite skiers. Article. J Sports Med Phys Fitness. Aug 2019;59(8):1339–1345. doi:10.23736/S0022-4707.19.09386-1 30758169 | Study design
670 | Lonnie M, Wadolowska L, Morze J, Bandurska-Stankiewicz E. Associations of Dietary-Lifestyle Patterns with Obesity and Metabolic Health: Two-Year Changes in MeDiSH((R)) Study Cohort. Int J Environ Res Public Health. Oct 21 2022;19(20)doi:10.3390/ijerph192013647 | Intervention or Exposure
671 | Looney SM, Raynor HA. Are changes in consumption of "healthy" foods related to changes in consumption of "unhealthy" foods during pediatric obesity treatment? Article. Int J Environ Res Public Health. Apr 2012;9(4):1368–78. doi:10.3390/ijerph9041368 22690199 | Intervention or Exposure
672 | Lopez CPR, Ramos-Terrones I, Lazarevich I, Metabolic syndrome, physical activity and eating habits in school children of the south of Mexico city. Article. Investigacion Clinica (Venezuela). 2019;60(1):7–19. | Study design; Intervention or Exposure
673 | Lopez-Bueno M, Fernandez-Aparicio A, Gonzalez-Jimenez E, Montero-Alonso MA, Schmidt-RioValle J. Self-Care by Muslim Women during Ramadan Fasting to Protect Nutritional and Cardiovascular Health. Article. Int J Environ Res Public Health. Nov 25 2021;18(23)doi: 10.3390/ijerph182312393 | Intervention or Exposure
674 | Lotfi MH, Fallahzadeh H, Rahmanian M, Association of food groups intake and physical activity with gestational diabetes mellitus in Iranian women. J Matern Fetal Neonatal Med. Nov 2020;33(21):3559–3564. doi: 10.1080/14767058.2019.1579189 30720376 | Study design; Intervention or Exposure
675 | Lowe C, Kelly M, Sarma H, The double burden of malnutrition and dietary patterns in rural Central Java, Indonesia. Lancet Reg Health West Pac. Sep 2021;14:100205. doi:10.1016/j.lanwpc.2021.100205 34671750 | Study design
676 | Loy SL, Cheung YB, Colega MT, Associations of Circadian Eating Pattern and Diet Duality with Substantial Postpartum Weight Retention. Nutrients. Nov 6 2019; 11(11)doi:10.3390/nu11112686 | Life stage
677 | Loy SL, Cheung YB, Marjorelee C, Maternal night-eating and lower diet quality during pregnancy are associated with substantial postpartum weight retention. Proceedings of the Nutrition Society. 2020;79(OCE2):E102–E102. doi: 10.1017/s0029665120000506 | Publication status
678 | Lugones-Sanchez C, Recio-Rodriguez Jl, Agudo-Conde C, Long-term Effectiveness of a Smartphone App Combined With a Smart Band on Weight Loss, Physical Activity, and Caloric Intake in a Population With Overweight and Obesity (Evident 3 Study): Randomized Controlled Trial. J Med Internet Res. Feb 1 2022;24(2):e30416. doi:10.2196/30416 35103609 | Intervention or Exposure; Comparator
679 | Lugones-Sanchez C, Recio-Rodriguez Jl, Menendez-Suarez M, Effect of a Multicomponent mHealth Intervention on the Composition of Diet in a Population with Overweight and Obesity-Randomized Clinical Trial EVIDENT 3. Nutrients. Jan 9 2022;14(2)doi: 10.3390/nu14020270 | Intervention or Exposure
680 | Lundkvist E, Stoltz Sjostrom E, Lundberg R, Silfverdal SA, West CE, Domellof M. Fruit Pouch Consumption and Dietary Patterns Related to BMIz at 18 Months of Age. Nutrients. Jun 30 2021;13(7)doi:10.3390/nu13072265 | Study design; Intervention or Exposure
681 | Luo M, Liu Y, Ye P, Weight-Control Behaviors and Dietary Intake in Chinese Adults: An Analysis of Three National Surveys (2002–2015). Nutrients. Mar 14 2023;15(6)doi:10.3390/nu15061395 | Study design; Outcome
682 | Luscher TF. Nutrition, obesity, diabetes, and cardiovascular outcomes: a deadly association. Article. Eur Heart J. Jul 21 2020;41 (28):2603–2607. doi: 10.1093/eurheartj/ehaa622 33216914 | Study design; Publication status
683 | Lyu JL, Liu Z, Zhou S, The Effect of a Multifaceted Intervention on Dietary Quality in Schoolchildren and the Mediating Effect of Dietary Quality between Intervention and Changes in Adiposity Indicators: A Cluster Randomized Controlled Trial. Nutrients. Aug 10 2022;14(16)doi:10.3390/nu14163272 | Intervention or Exposure; Comparator
684 | Ma E, Ohira T, Yasumura S, Development of a Japanese Healthy Diet Index: The Fukushima Health Management Survey 2011. Int J Environ Res Public Health. Nov 11 2022;19(22)doi:10.3390/ijerph192214858 | Study design
685 | Ma L, Fang Z, Gao L, A 3-year Longitudinal Study of Pocket Money, Eating Behavior, Weight Status: The Childhood Obesity Study in China Mega-Cities. Article. Int J Environ Res Public Health. Dec 7 2020;17(23):1–13. doi: 10.3390/ijerph17239139 | Intervention or Exposure
686 | Ma Y, Li R, Zhan W, Role of BMI in the Relationship Between Dietary Inflammatory Index and Depression: An Intermediary Analysis. Article. Front Med (Lausanne). 2021;8:748788. doi:10.3389/fmed.2021.748788 34869441 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
687 | Mabli J, Bleeker M, Fox MK, Jean-Louis B, Fox M. Randomized Controlled Trial of Healthy Harlem's Get Fit Program: An After-School Intervention for Childhood Overweight and Obesity in the Harlem Children's Zone. Article. Child Obes. Oct 2020;16(7):479–487. doi: 10.1089/chi.2020.0012 33030989 | Intervention or Exposure
688 | Mabry-Hernandez IR, Legg M. Behavioral Counseling Interventions for Healthy Weight and Weight Gain in Pregnancy. Article. Am Fam Physician. Feb 1 2022;105(2):187–188.35166501 | Study design
689 | Mack I, Reiband N, Etges C, The Kids Obesity Prevention Program: Cluster Randomized Controlled Trial to Evaluate a Serious Game for the Prevention and Treatment of Childhood Obesity. J Med Internet Res. Apr 24 2020;22(4):e15725. doi: 10.2196/15725 32329742 | Intervention or Exposure; Duration of Intervention; Outcome
690 | Mackeen AD, Young AJ, Lutcher S, Encouraging appropriate gestational weight gain in high-risk gravida: A randomized controlled trial. Article. Obes Sci Pract. Jun 2022;8(3):261–271. doi:10.1002/osp4.565 35664244 | Intervention or Exposure; Comparator
691 | Macknin M, Stegmeier N, Thomas A, Three Healthy Eating Patterns and Cardiovascular Disease Risk Markers in 9 to 18 Year Olds With Body Mass Index >95%: A Randomized Trial. Clin Pediatr (Phila). Oct 2021;60(11–12):474–484. doi: 10.1177/00099228211044841 34546139 | Study design
692 | Madalosso MM, Schaan B, Cureau FV. Association between Body Weight Perception and Quality of Diet in Brazilian Adolescents. Rev Paul Pediatr. 2020;38:e2020057. doi:10.1590/1984-0462/2020/38/2020057 33331596 | Study design; Intervention or Exposure; Outcome
693 | Maddison R, Hargreaves EA, Wyke S, Rugby Fans in Training New Zealand (RUFIT-NZ): a pilot randomized controlled trial of a healthy lifestyle program for overweight men delivered through professional rugby clubs in New Zealand. BMC Public Health. Feb 8 2019;19(1):166. doi:10.1186/S12889-019-6472-3 30736781 | Intervention or Exposure
694 | Maddock J, Ambrosini GL, Griffin JL, A dietary pattern derived using B-vitamins and its relationship with vascular markers over the life course. Article. Clin Nutr. Jun 2019;38(3):1464–1473. doi:10.1016/j.clnu.2018.06.969 30005901 | Outcome
695 | Madencioglu S, Yucecan S. The Relationship Between Adherence to the Mediterranean Diet and Body Composition in Nutrition and Dietetic Students. Proceedings of the Nutrition Society. 2020;79(OCE2):1–1.31985390 | Publication status
696 | Madlala HP, Steyn NP, Kalk E, Association between food intake and obesity in pregnant women living with and without HIV in Cape Town, South Africa: a prospective cohort study. BMC Public Health. Aug 4 2021;21(1):1504. doi: 10.1186/s12889-021-11566-2 34348683 | Intervention or Exposure
697 | Madrigal C, Soto-Mendez MJ, Hernandez-Ruiz A, Energy Intake, Macronutrient Profile and Food Sources of Spanish Children Aged One to <10 Years-Results from the EsNuPI Study. Article. Nutrients. Mar 25 2020;12(4):1–26. doi:10.3390/nu12040893 | Study design; Intervention or Exposure
698 | Magkos F, Rasmussen SI, Hjorth MF, Unprocessed red meat in the dietary treatment of obesity: a randomized controlled trial of beef supplementation during weight maintenance after successful weight loss. Am J Clin Nutr. Dec 19 2022;116(6):1820–1830. doi: 10.1093/ajcn/nqac152 36307956 | Intervention or Exposure - Foods/Beverages Not Reported
699 | Mahmoudinezhad M, Abbasalizad Farhangi M. Association between Ag-RP, alpha-MSH and cardiovascular risk factors regarding adherence to diet quality index-international (DQI-I) among obese individuals. J Cardiovasc Thorac Res. 2021;13(4):320–329. doi: 10.34172/jcvtr.2021.48 35047137 | Study design
700 | Mai TMT, Tran QC, Nambiar S, Gallegos D, Van der Pols JC. Dietary patterns and child, parental, and societal factors associated with being overweight and obesity in Vietnamese children living in Ho Chi Minh city. Matern Child Nutr. Jan 2024;20 Suppl 2(Suppl 2):e13514. doi:10.1111/mcn.13514 37010142 | Study design
701 | Makama M, Earnest A, Lim S, Assessing patterns of change in lifestyle behaviours by parity: a longitudinal cohort study. Int J Epidemiol. Apr 19 2023;52(2):589–599. doi: 10.1093/ije/dyac139 35776100 | Intervention or Exposure; Outcome; Comparator
702 | Makarem N, Chau K, Miller EC, Association of a Mediterranean Diet Pattern With Adverse Pregnancy Outcomes Among US Women. JAMA Netw Open. Dec 1 2022;5(12):e2248165. doi:10.1001/jamanetworkopen.2022.48165 36547978 | Outcome
703 | Maki KC, Wilcox ML, Dicklin MR, Substituting Lean Beef for Carbohydrate in a Healthy Dietary Pattern Does Not Adversely Affect the Cardiometabolic Risk Factor Profile in Men and Women at Risk for Type 2 Diabetes. J Nutr. Jul 1 2020;150(7):1824–1833. doi:10.1093/jn/nxaa116 32359153 | Duration of Intervention
704 | Makura-Kankwende CBT, Gradidge PJ, Crowther NJ, Norris SA, Chikowore T. Nutrient Patterns and Body Composition Parameters of Black South African Women. Nutrients. Dec 22 2020;13(1)doi:10.3390/nu13010006 | Study design
705 | Maldonado LE, Farzan SF, Toledo-Corral CM, A Vegetable, Oil, and Fruit Dietary Pattern in Late Pregnancy is Linked to Reduced Risks of Adverse Birth Outcomes in a Predominantly Low-Income Hispanic and Latina Pregnancy Cohort. J Nutr. Jan 14 2023;152(12):2837–2846. doi: 10.1093/jn/nxac209 36055799 | Outcome
706 | Malinowska AM, Schmidt M, Chmurzynska A. Diet quality, anthropometries, and gut microbiota composition in healthy adults. Proceedings of the Nutrition Society. 2020;79(OCE2):E369–E369. doi:10.1017/s0029665120003171 | Publication status
707 | Maltaric M, Ruscic P, Kolak M, Adherence to the Mediterranean Diet Related to the Health Related and Well-Being Outcomes of European Mature Adults and Elderly, with an Additional Reference to Croatia. Int J Environ Res Public Health. Mar 10 2023;20(6)doi:10.3390/ijerph20064893 | Study design
708 | Man S, Zheng FY, Li SX, Benefit-Risk Assessment of Dietary Patterns by Bioavailable Metals, Gut Microbes, and Their Interaction for Human Health. J Agric Food Chem. Aug 10 2022;70(31):9769–9778. doi:10.1021/acs.jafc.2c02829 35895310 | Intervention or Exposure; Outcome
709 | Mancioppi V, Solito A, Ricotti R, Good-day: efficacy of gamification of an educational training to mediterranean diet on weight and metabolic control in paediatric obesity, preliminary data at 6 months. Journal: Conference Abstract. High blood pressure & cardiovascular prevention. 2019;26(2):171–172. | Publication status
710 | Mangels R. "Healthy Plant Foods" Associated With Less Weight Gain Over Time. Vegetarian Journal. 2020;39(2):14–14. | Health Status; Publication status
711 | Manohar N, Hayen A, Scott JA, Do LG, Bhole S, Arora A. Impact of Dietary Trajectories on Obesity and Dental Caries in Preschool Children: Findings from the Healthy Smiles Healthy Kids Study. Nutrients. Jun 29 2021;13(7)doi:10.3390/nu13072240 | Intervention or Exposure
712 | Marcano-Olivier M, Sallaway-Costello J, McWilliams L, Horne PJ, Viktor S, Erjavec M. Changes in the nutritional content of children's lunches after the Food Dudes healthy eating programme. J Nutr Sci. 2021;10:e40. doi: 10.1017/jns.2021.31 34367625 | Intervention or Exposure; Outcome
713 | Marinho AR, Severo M, Vilela S, Torres D, Oliveira A, Lopes C. Association of dietary macronutrient intake with adiposity during childhood according to sex: Findings from the generation XXI birth cohort. Pediatr Obes. Sep 2022;17(9):e12916. doi: 10.1111/ijpo.12916 35478450 | Intervention or Exposure
714 | Marked J, Herget S, Petroff D, Telephone-based adiposity prevention for families with overweight children (T.A.F.F.-Study): one year outcome of a randomized, controlled trial. Article. Int J Environ Res Public Health. Oct 3 2014;11(10):10327–44. doi:10.3390/ijerph111010327 25286167 | Intervention or Exposure
715 | Maroto-Rodriguez J, Delgado-Velandia M, Ortola R, A Mediterranean Lifestyle and Frailty Incidence in Older Adults: The Seniors-ENRICA-1 Cohort. J Gerontol A Biol Sci Med Sci. Sep 1 2022;77(9):1845–1852. doi:10.1093/gerona/glab292 34614144 | Intervention or Exposure; Outcome
716 | Marsigliante S, Ciardo V, Di Maglie A, My G, Muscella A. Efficacy of school-based intervention programs in reducing overweight: A randomized trial. Front Nutr. 2022;9:1001934. doi:10.3389/fnut.2022.1001934 36245531 | Intervention or Exposure
717 | Martin JC, Moran LJ, Teede HJ, Ranasinha S, Lombard CB, Harrison CL. Diet Quality in a Weight Gain Prevention Trial of Reproductive Aged Women: A Secondary Analysis of a Cluster Randomized Controlled Trial. Article. Nutrients. Dec 27 2018;11(1)doi:10.3390/nu11010049 | Size or Power
718 | Martincrespo-Blanco MC, Varillas-Delgado D, Blanco-Abril S, Cid-Exposito MG, Robledo-Martin J. Effectiveness of an Intervention Programme on Adherence to the Mediterranean Diet in a Preschool Child: A Randomised Controlled Trial. Article. Nutrients. Apr 7 2022;14(8)doi:10.3390/nu14081536 | Comparator
719 | Martinez-Arroyo A, Cantor E, Fisberg RM, Corvalan C. Lower adherence to a prudent dietary pattern is associated with earlier age at menarche in adolescents from the Growth and Obesity Chilean Cohort Study. Front Public Health. 2022; 10:995593. doi: 10.3389/fpubh.2022.995593 36793361 | Outcome
720 | Martinez-Perez C, San-Cristobal R, Guallar-Castillon P, Use of Different Food Classification Systems to Assess the Association between Ultra-Processed Food Consumption and Cardiometabolic Health in an Elderly Population with Metabolic Syndrome (PREDIMED-Plus Cohort). Article. Nutrients. Jul 20 2021;13(7)doi: 10.3390/nu13072471 | Study design
721 | Martinez-Rodriguez A, Cuestas-Calero BJ, Martinez-Olcina M, Marcos-Pardo PJ. Benefits of Adding an Aquatic Resistance Interval Training to a Nutritional Education on Body Composition, Body Image Perception and Adherence to the Mediterranean Diet in Older Women. Journal: Article. Nutrients. Aug 6 2021;13(8)doi:10.3390/nu13082712 | Intervention or Exposure; Comparator
722 | Martinez-Rodriguez A, Vidal-Martinez L, Martinez-Olcina M, Study the Effect of an Innovative Educational Program Promoting Healthy Food Habits on Eating Disorders, Mediterranean Diet Adherence and Body Composition in University Students. Healthcare (Basel). Mar 28 2023;11(7)doi:10.3390/healthcare11070965 | Intervention or Exposure
723 | Martinez-Rodriguez, Loaiza-Martinez, Sanchez-Sanchez, Psychological, Physiological, and Physical Effects of Resistance Training and Personalized Diet in Celiac Women.. Frontiers in nutrition. 2022. 9.doi:10.3389/fnut.2022.838364 | Intervention or Exposure
724 | Martini GL, Pinto RS, Brusco CM, Similar body composition, muscle size, and strength adaptations to resistance training in lacto-ovo-vegetarians and non-vegetarians. Appl Physiol Nutr Metab. Jun 1 2023;48(6):469–478. doi: 10.1139/apnm-2022-0258 36857740 | Intervention or Exposure
725 | Masip G, Keski-Rahkonen A, Pietilainen KH, Development of a Food-Based Diet Quality Score from a Short FFQ and Associations with Obesity Measures, Eating Styles and Nutrient Intakes in Finnish Twins. Nutrients. Oct 23 2019;11(11)doi:10.3390/nu11112561 | Study design
726 | Masley S. Why the Mediterranean Diet Is the Best Diet on the Planet. Holistic Primary Care. Spring2020 2020;21(1):8–9. | Study design; Publication status
727 | Massini G, Capra N, Buganza R, Nyffenegger A, de Sanctis L, Guardamagna O. Mediterranean Dietary Treatment in Hyperlipidemic Children: Should It Be an Option? Article. Nutrients. Mar 23 2022;14(7)doi:10.3390/nu14071344 | Study design; Comparator
728 | Mateo-Orcajada A, Vaquero-Cristobal R, Montoya-Lozano JM, Abenza-Cano L. Differences in Kinanthropometric Variables and Physical Fitness of Adolescents with Different Adherence to the Mediterranean Diet and Weight Status: "Fat but Healthy Diet" Paradigm. Nutrients. Feb 24 2023;15(5)doi:10.3390/nu15051152 | Study design
729 | Mathew SM, Bell LK, Mauch C, Magarey AM. Weight status and diets of children aged 1–12 years attending a tertiary public paediatric outpatient clinic. J Paediatr Child Health. Jan 2020;56(1):47–54. doi: 10.1111/jpc.14489 31077483 | Study design
730 | Matsumoto S, Beeson WL, Shavlik DJ, Association between vegetarian diets and cardiovascular risk factors in non-Hispanic white participants of the Adventist Health Study-2. Article in Press. Journal of Nutritional Science. 2019; | Study design
731 | Mattavelli E, Olmastroni E, Casula M, Adherence to Mediterranean Diet: A Population-Based Longitudinal Cohort Study. Nutrients. Apr 12 2023;15(8)doi:10.3390/nu15081844 | Outcome
732 | Maugeri A, Barchitta M, Favara G, Maternal dietary patterns are associated with pre-pregnancy body mass index and gestational weight gain: Results from the “mamma & bambino” cohort. Article. Nutrients. 2019; 11 (6) | Data overlap
733 | Mazurkiewicz D, Bronkowska M. Circulating Insulin and IGF-1 and Frequency of Food Consumption during Pregnancy as Predictors of Birth Weight and Length. Nutrients. Jul 9 2021;13(7):2344-2344. doi:10.3390/nu13072344 34371854 | Intervention or Exposure
734 | McCormick DP, Reyna L, Reifsnider E. Calories, Caffeine and the Onset of Obesity in Young Children. Acad Pediatr. Aug 2020;20(6):801–808. doi:10.1016/j.acap.2020.02.014 32081767 | Intervention or Exposure
735 | McCullough D, Harrison T, Lane K, The effect of a low carbohydrate high fat diet on apolipoproteins and cardiovascular risk. Journal: Conference Abstract. Proceedings of the Nutrition Society. 2020;79(OCE2):E677–E677. doi:10.1017/s0029665120006266 | Duration of Intervention; Publication status
736 | McElfish PA, Felix HC, Bursae Z, A Cluster Randomized Controlled Trial Comparing Diabetes Prevention Program Interventions for Overweight/Obese Marshallese Adults. Article. Inquiry. Jan-Dec 2023;60:469580231152051. doi: 10.1177/00469580231152051 36799349 | Intervention or Exposure - Foods/Beverages Not Reported
737 | McEvoy CT, Moore S, Erwin C, Trial to Encourage Adoption and Maintenance of a MEditerranean Diet (TEAM-MED): a randomised pilot trial of a peer support intervention for dietary behaviour change in adults from a Northern European population at high CVD risk. Br J Nutr. Oct 14 2022;128(7):1322–1334. doi:10.1017/S0007114521003986 34605384 | Size or Power
738 | McGee M, Unger S, Hamilton J, Associations between Diet Quality and Body Composition in Young Children Born with Very Low Body Weight. J Nutr. Nov 19 2020;150(11):2961–2968. doi:10.1093/jn/nxaa281 33025010 | Study design; Health Status
739 | McNitt KM, Hohman EE, Rivera DE, Underreporting of Energy Intake Increases over Pregnancy: An Intensive Longitudinal Study of Women with Overweight and Obesity. Article. Nutrients. Jun 1 2022;14(11)doi:10.3390/nu14112326 | Intervention or Exposure
740 | Meadley B, Wolkow AP, Smith K, Perraton L, Bowles KA, Bonham MP. Cardiometabolic, Dietary and Physical Health in Graduate Paramedics during the First 12-Months of Practice - A Longitudinal Study. Prehosp Emerg Care. Jul-Aug 2022;26(4):524–536. doi: 10.1080/10903127.2021.1949081 34232788 | Study design; Intervention or Exposure; Outcome
741 | Mears M, Tussing-Humphreys L, Cerwinske L, Associations between alternate healthy eating index-2010, body composition, osteoarthritis severity, and interleukin-6 in older overweight and obese african american females with self-reported osteoarthritis. Article. Nutrients. 2019;11(1) | Study design
742 | Mehrdad M, Vahid F, Shivappa N, Hebert JR, Fardaei M, Hassan Eftekhari M. High dietary inflammatory index (Dll) scores increase odds of overweight in adults with rs9939609 polymorphism of FTO gene. Clin Nutr ESPEN. Apr 2021;42:221–226. doi:10.1016/j.clnesp.2021.01.034 | Intervention or Exposure - Foods/Beverages Not Reported
743 | Mei S, Ding J, Wang K, Ni Z, Yu J. Mediterranean Diet Combined With a Low-Carbohydrate Dietary Pattern in the Treatment of Overweight Polycystic Ovary Syndrome Patients. Front Nutr. 2022;9:876620. doi:10.3389/fnut.2022.876620 35445067 | Intervention or Exposure - Foods/Beverages Not Reported
744 | Meinila J, Perala MM, Kanerva N, Birth weight modifies the association between a healthy Nordic diet and office blood pressure in old age. J Hum Hypertens. Oct 2021;35(10):849–858. doi:10.1038/s41371-020-00423-1 33051584 | Outcome
745 | Meinila J, Valkama A, Koivusalo SB, Association between diet quality measured by the Healthy Food Intake Index and later risk of gestational diabetes-a secondary analysis of the RADIEL trial. Article. Eur J Clin Nutr. Apr 2017;71(4):555–557. doi:10.1038/ejcn.2016.275 28145421 | Outcome; Data overlap
746 | Melero V, Assaf-Balut C, Torre NG, Benefits of Adhering to a Mediterranean Diet Supplemented with Extra Virgin Olive Oil and Pistachios in Pregnancy on the Health of Offspring at 2 Years of Age. Results of the San Carlos Gestational Diabetes Mellitus Prevention Study. J Clin Med. May 13 2020;9(5)doi:10.3390/jcm9051454 | Data overlap
747 | Melero V, Garcia de la Torre N, Assaf-Balut C, Effect of a Mediterranean Diet-Based Nutritional Intervention on the Risk of Developing Gestational Diabetes Mellitus and Other Maternal-Fetal Adverse Events in Hispanic Women Residents in Spain. Article. Nutrients. Nov 14 2020;12(11):1–14. doi:10.3390/nu12113505 | Outcome
748 | Mendham A, Brooks NE, Micklesfield LK, Osteoporosis in older black South African women and relationships with body composition, dietary intake and physical activity. Proceedings of the Nutrition Society. 2020;79(OCE2):1–1.31985390 | Publication status
749 | Menichini D, Petrella E, Dipace V, Di Monte A, Neri I, Facchinetti F. The Impact of an Early Lifestyle Intervention on Pregnancy Outcomes in a Cohort of Insulin-Resistant Overweight and Obese Women. Nutrients. May 21 2020;12(5)doi:10.3390/nu12051496 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
750 | Mennella JA, Smethers AD, Decker JE, Delahanty MT, Stallings VA, Trabulsi JC. Effects of Early Weight Gain Velocity, Diet Quality, and Snack Food Access on Toddler Weight Status at 1.5 Years: Follow-Up of a Randomized Controlled Infant Formula Trial. Article. Nutrients. Nov 4 2021;13(11)doi:10.3390/nu13113946 | Intervention or Exposure
751 | Merino J, Guasch-Ferre M, Li J, Polygenic scores, diet quality, and type 2 diabetes risk: An observational study among 35,759 adults from 3 US cohorts. Article. PLoS Med. Apr 2022;19(4):e1003972. doi: 10.1371/journal.pmed.1003972 35472203 | Outcome
752 | Merrotsy A, McCarthy AL, Lacey S, Coppinger T. Identifying dietary patterns in Irish schoolchildren and their association with nutritional knowledge and markers of health before and after intervention. Br J Nutr. Aug 14 2021;126(3):383–391. doi: 10.1017/S0007114520004043 33054881 | Study design
753 | Mertens E, Colizzi C, Penalvo JL. Ultra-processed food consumption in adults across Europe. Eur J Nutr. Apr 2022;61(3):1521–1539. doi: 10.1007/S00394-021-02733-7 34862518 | Study design; Intervention or Exposure
754 | Metro D, Papa M, Manasseri L, Mediterranean diet in a Sicilian student population. Second part: breakfast and its nutritional profile. Nat Prod Res. Aug 2020;34(16):2255–2261. doi:10.1080/14786419.2018.1452016 29553811 | Study design; Intervention or Exposure
755 | Miele MJ, Souza RT, Calderon IM, Maternal Nutrition Status Associated with Pregnancy-Related Adverse Outcomes. Nutrients. Jul 13 2021;13(7)doi:10.3390/nu13072398 | Outcome
756 | Mikes O, Brantsaeter AL, Knutsen HK, Dietary patterns and birth outcomes in the ELSPAC pregnancy cohort. J Epidemiol Community Health. Jun 2022;76(6):613–619. doi:10.1136/jech-2020-215716 34921058 | Outcome
757 | Miles FL, Lloren JIC, Haddad E, Plasma, urine, and adipose tissue biomarkers of dietary intake differ between vegetarian and non-vegetarian diet groups in the Adventist Health Study-2. Article. Journal of Nutrition. 2019;149(4):667–675.30770530 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
758 | Miller C, Boushey C, Benny P, Diet quality predicts hypertensive disorders of pregnancy in Asian and Pacific Islander Cohort. Nutr Health. Jun 2024;30(2):243–252. doi: 10.1177/02601060221109668 35754336 | Outcome
759 | Miller CK, King D, Nagaraja HN, Fujita K, Cheavens J, Focht BC. Impact of an augmented intervention on self-regulatory, dietary and physical activity outcomes in a diabetes prevention trial among adults with prediabetes. J Behav Med. Oct 2023;46(5):770–780. doi: 10.1007/s10865-023-00406-w 36933057 | Intervention or Exposure
760 | Miller CK, Nagaraja HN, Cheavens JS, Fujita K, Lazarus SA, Brunette DS. Sex Differences in Early Weight Loss Success During a Diabetes Prevention Intervention. Am J Health Behav. Apr 30 2023;47(2):337–348. doi:10.5993/AJHB.47.2.13 37226352 | Intervention or Exposure; Duration of Intervention
761 | Miller NA, Ehmann MM, Hagerman CJ, Sharing digital self-monitoring data with others to enhance long-term weight loss: A randomized controlled trial. Contemp Clin Trials. Jun 2023;129:107201. doi:10.1016/j.cct.2023.107201 37080355 | Study design; Publication status
762 | Minato-lnokawa S, Hayashi I, Nirengi S, Association of Dietary Change during Pregnancy with Large-for-Gestational Age Births: A Prospective Observational Study. J Nutr Sci Vitaminol (Tokyo). 2020;66(3):246–254. doi:10.3177/jnsv.66.246 32612087 | Intervention or Exposure
763 | Mintjens S, van Poppel MNM, Groen H, The Effects of a Preconception Lifestyle Intervention on Childhood Cardiometabolic Health-Follow-Up of a Randomized Controlled Trial. Article. Cells. Dec 24 2021;11 (1)doi: 10.3390/cells11010041 | Intervention or Exposure; Outcome
764 | Miralles-Amoros L, Asencio-Mas N, Martinez-Olcina M, Study the Effect of Relative Energy Deficiency on Physiological and Physical Variables in Professional Women Athletes: A Randomized Controlled Trial. Metabolites. Jan 23 2023;13(2)doi: 10.3390/metabo13020168 | Size or Power
765 | Miranda-Penarroya G, Zeron-Rugerio MF, Vallejo-Gracia M, Sorio-Fuentes R, Saenger-Ruiz F, Izquierdo-Pulido M. Adherence to Healthy Lifestyle Habits Is a Determinant of the Effectiveness of Weight Loss among Patients Undergoing Endoscopic Bariatric Therapies. Article. Nutrients. May 28 2022;14(11)doi:10.3390/nu14112261 | Intervention or Exposure; Health Status
766 | Mirmiran P, Bakhshi B, Hosseinpour-Niazi S, Sarbazi N, Hejazi J, Azizi F. Does the association between patterns of fruit and vegetables and metabolic syndrome incidence vary according to lifestyle factors and socioeconomic status? Nutr Metab Cardiovasc Dis. Jul 24 2020;30(8):1322–1336. doi:10.1016/j.numecd.2020.04.008 32513582 | Intervention or Exposure; Outcome
767 | Mirmiran P, Farhadnejad H, Teymoori F, Parastouei K, Azizi F. The higher adherence to healthy lifestyle factors is associated with a decreased risk of metabolic syndrome in Iranian adults. Nutrition Bulletin. 2022;47(1):57–67.36045083 | Intervention or Exposure
768 | Mirmiran P, Hosseini-Esfahani F, Esfandiar Z, Hosseinpour-Niazi S, Azizi F. Associations between dietary antioxidant intakes and cardiovascular disease. Sci Rep. Jan 27 2022;12(1):1504. doi:10.1038/s41598-022-05632-x 35087166 | Intervention or Exposure
769 | Mirmiran P, Hosseinpour-Niazi S, Moghaddam-Banaem L, Lamyian M, Goshtasebi A, Azizi F. Inverse relation between fruit and vegetable intake and the risk of gestational diabetes mellitus. Article. International Journal for Vitamin and Nutrition Research. 2019;89(1–2):37–44.31188080 | Intervention or Exposure
770 | Mirmiran P, Ziadlou M, Karimi S, Hosseini-Esfahani F, Azizi F. The association of dietary patterns and adherence to WHO healthy diet with metabolic syndrome in children and adolescents: Tehran lipid and glucose study. Article. BMC Public Health. Nov 6 2019;19(1):1457. doi:10.1186/s12889-019-7779-9 31694610 | Intervention or Exposure; Outcome
771 | Mistretta A, Marventano S, Zappala G, Currenti W, Matalone M, Marranzano M. Relation between out-of-home eating and weight status in adolescents living in Sicily, southern Italy. Journal: Article. Progress in nutrition. 2019;21:57–64. | Study design
772 | Mitchell A, Fall T, Melhus H, Wolk A, Michaelsson K, Byberg L. Is the effect of Mediterranean diet on hip fracture mediated through type 2 diabetes mellitus and body mass index? Int J Epidemiol. Mar 3 2021;50(1):234–244. doi:10.1093/ije/dyaa239 33367703 | Outcome; Comparator
773 | Mitchell ES, Yang Q, Ho AS, Self-Reported Nutritional Factors Are Associated with Weight Loss at 18 Months in a Self-Managed Commercial Program with Food Categorization System: Observational Study. Nutrients. May 20 2021;13(5)doi:10.3390/nu13051733 | Study design; Size or Power
774 | Mitku AA, Zewotir T, North D, Jeena P, Naidoo RN. The differential effect of maternal dietary patterns on quantiles of Birthweight. BMC Public Health. Jun 22 2020;20(1):976. doi:10.1186/s12889-020-09065-x 32571268 | Outcome
775 | Mitra SR, Tan PY. Effect of an individualised high-protein, energy-restricted diet on anthropometric and cardio-metabolic parameters in overweight and obese Malaysian adults: a 6-month randomised controlled study. Article. Br J Nutr. May 2019;121(9):1002–1017. doi: 10.1017/S0007114519000345 30761964 | Intervention or Exposure - Foods/Beverages Not Reported
776 | Mohammadisima N, Farshbaf-Khalili A, Ostadrahimi A, Pourmoradian S. Positive relation between dietary inflammatory index and osteoporosis in postmenopausal women. Int J Vitam Nutr Res. Apr 2024;94(2):86–94. doi:10.1024/0300-9831/a000773 36530143 | Study design
777 | Mohorko N, Cernelic-Bizjak M, Poklar-Vatovec T, Weight loss, improved physical performance, cognitive function, eating behavior, and metabolic profile in a 12-week ketogenic diet in obese adults. Article. Nutr Res. Feb 2019;62:64–77. doi:10.1016/j.nutres.2018.11.007 30803508 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
778 | Mohsenzadeh-Ledari F, Motaghi Z, Taghizadeh Z, Effect of Motivational Interviewing, Dietary Advice, and Physical Activity on Fetal-Neonatal Outcome in Pregnant Women with Metabolic Syndrome: a Randomized Controlled Trial. Journal article. Journal of mazandaran university of medical sciences. 2022;32(214):124–133. | Language
779 | Mohsenzadeh-Ledari F, Taghizadeh Z, Motaghi Z, Effect of caring intervention on preeclampsia in pregnant women with metabolic syndrome: A randomized controlled trial. Journal of Nursing & Midwifery Sciences. 2022;9(1):8–15. | Intervention or Exposure; Country; Comparator
780 | Mokhtari E, Farhadnejad H, Teymoori F, Mirmiran P, Azizi F. The association of insulinemic potential of diet and lifestyle with the risl of insulin-related disorders: a prospective cohort study among participants of Tehran Lipid and Glucose Study. Article. Diabetol MetabSyndr. May 13 2021;13(1):53. doi:10.1186/s13098-021-00674-z | Outcome
781 | Mompeo O, Freidin MB, Gibson R, Genome-Wide Association Analysis of Over 170,000 Individuals from the UK Biobank Identifies Seven Loci Associated with Dietary Approaches to Stop Hypertension (DASH) Diet. Nutrients. Oct 21 2022;14(20)doi: 10.3390/nu14204431 | Study design
782 | Monserrat-Mesquida M, Quetglas-Llabres M, Bouzas C, Effects of 2-Year Nutritional and Lifestyle Intervention on Oxidative and Inflammatory Statuses in Individuals of 55 Years of Age and over at High Cardiovascular Risk. Antioxidants (Basel). Jul 5 2022;11(7)doi: 10.3390/antiox11071326 | Intervention or Exposure; Comparator
783 | Montemayor S, Mascara CM, Ugarriza L, Adherence to Mediterranean Diet and NAFLD in Patients with Metabolic Syndrome: The FLIPAN Study. Nutrients. Aug 3 2022;14(15)doi:10.3390/nu14153186 | Size or Power
784 | Morales-Suarez-Varela M, Peraita-Costa I, Perales-Marin A, Marcos Puig B, Llopis-Morales J, Pico Y. Effect of Adherence to the Mediterranean Diet on Maternal Iron Related Biochemical Parameters during Pregnancy and Gestational Weight Gain. Life (Basel). May 8 2023;13(5)doi: 10.3390/life13051138 | Study design
785 | Moran LJ, Noakes M, Clifton P, Predictors of Lifestyle Intervention Attrition or Weight Loss Success in Women with Polycystic Ovary Syndrome Who Are Overweight or Obese. Article. Nutrients. Feb 26 2019;11(3)doi:10.3390/nu11030492 | Intervention or Exposure
786 | Moran-Lev H, Cohen S, Zelber-Sagi S, Effect of Coffee and Tea Consumption on Adolescent Weight Control: An Interventional Pilot Study. Child Obes. Mar 2023;19(2):121–129. doi:10.1089/chi.2022.0032 35639365 | Intervention or Exposure
787 | Mora-Urda Al, Martin-Almena FJ, Montero Lopez MDP. Relationship between the Dietary Inflammatory Index and Cardiovascular Health among Children. Int J Environ Res Public Health. Nov 25 2022;19(23)doi:10.3390/ijerph192315706 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
788 | Morelli C, Avolio E, Galluccio A, Nutrition Education Program and Physical Activity Improve the Adherence to the Mediterranean Diet: Impact on Inflammatory Biomarker Levels in Healthy Adolescents From the DIMENU Longitudinal Study. Front Nutr. 2021;8:685247. doi:10.3389/fnut.2021.685247 34350206 | Outcome; Comparator
789 | Morin E, Michaud-Letourneau I, Couturier Y, Roy M. A whole-food, plant-based nutrition program: Evaluation of cardiovascular outcomes and exploration of food choices determinants. Article. Nutrition. Oct 2019;66:54–61. doi:10.1016/j.nut.2019.03.020 31207440 | Study design
790 | Moslehi N, Rahimi Sakak F, Mahdavi M, Mirmiran P, Azizi F. Visceral adiposity-related dietary patterns and the risk of cardiovascular disease in Iranian adults: A population-based cohort study. Front Nutr. 2022;9:812701. doi:10.3389/fnut.2022.812701 35967797 | Outcome
791 | Most J, Altazan AD, St Amant M, Beyl RA, Ravussin E, Redman LM. Increased Energy Intake After Pregnancy Determines Postpartum Weight Retention in Women With Obesity. J Clin Endocrinol Metab. Apr 1 2020;105(4):e1601–11. doi: 10.1210/clinem/dgz330 31905403 | Outcome
792 | Most J, Rebello CJ, Altazan AD, Martin CK, Amant MS, Redman LM. Behavioral Determinants of Objectively Assessed Diet Quality in Obese Pregnancy. Article. Nutrients. Jun 26 2019;11(7)doi:10.3390/nu11071446 | Study design; Outcome
793 | Motadi SA, Khorommbi T, Maluleke L, Mugware A, Mushaph L. Nutritional status and dietary pattern of the elderly in Thulamela Municipality of Vhembe District. Afr J Prim Health Care Fam Med. Nov 3 2022;14(1):e1–e8. doi:10.4102/phcfm.v14i1.3439 | Study design
794 | Mousavi SM, Ejtahed HS, Marvasti FE, The Effect of a Moderately Restricted Carbohydrate Diet on Cardiometabolic Risk Factors in Overweight and Obese Women With Metabolic Syndrome: A Randomized Controlled Trial. Article in Press. Clin Ther. Mar 2023;45(3):e103–e114. doi:10.1016/j.clinthera.2023.02.002 36872171 | Intervention or Exposure - Foods/Beverages Not Reported; Health Status- 100% CVD
795 | Mousavizadeh Z, Hosseini-Esfahani F, Javadi A, The interaction between dietary patterns and melanocortin-4 receptor polymorphisms in relation to obesity phenotypes. Obes Res Clin Pract. May-Jun 2020;14(3):249–256. doi:10.1016/j.orcp.2020.04.002 32446744 | Comparator
796 | Mueller J, Richards R, Jones RA, Supporting Weight Management during COVID-19: A Randomized Controlled Trial of a Web-Based, ACT-Based, Guided Self-Help Intervention. Article. Obes Facts. 2022;15(4):550–559. doi: 10.1159/000524031 35417910 | Intervention or Exposure
797 | Munda A, Starcic Erjavec M, Molan K, Ambrozic Avgustin J, Zgur-Bertok D, Pongrac Barlovic D. Association between pre-pregnancy body weight and dietary pattern with large-for-gestational-age infants in gestational diabetes. Article. Diabetology and Metabolic Syndrome. 2019;11(1) | Health Status- 100% Diabetes
798 | Muniz S, Barbieri MA, Sanches GF, Dietary pattern changes, obesity and excess body fat in adults of a Brazilian birth cohort. J Hum Nutr Diet. Feb 2023;36(1):191–202. doi:10.1111/jhn.13049 35722666 | Country
799 | Murff HJ. In patients with CHD, a Mediterranean vs. low-fat diet reduced major CV events at 7 y. Article in Press. Ann Intern Med. Sep 2022;175(9):JC100. doi:10.7326/J22-0061 36063545 | Health Status- 100% CVD
800 | Murphy J. Exercise, healthy diet in midlife may prevent serious health conditions in senior years. 2021. | Study design; Publication status
801 | Muscogiuri G, Barrea L, Di Somma C, Patient empowerment and the Mediterranean diet as a possible tool to tackle prediabetes associated with overweight or obesity: a pilot study. Article. Hormones. 2019;18(1):75–84.30644069 | Study design
802 | Mustafa S, Harding J, Wall C, Crowther C. Sociodemographic Factors Associated with Adherence to Dietary Guidelines in Women with Gestational Diabetes: A Cohort Study. Article. Nutrients. May 31 2021;13(6)doi:10.3390/nu13061884 | Study design; Health Status
803 | Mustafa ST, Harding JE, Wall CR, Crowther CA. Adherence to Clinical Practice Guideline Recommendations in Women with Gestational Diabetes and Associations with Maternal and Infant Health-A Cohort Study. Nutrients. Mar 17 2022;14(6):1274. doi:10.3390/nu14061274 35334931 | Health Status- 100% Diabetes; Outcome
804 | Muzsik A, Bajerska J, Jelen HH, Walkowiak J, Krzyzanowska-Jankowska P, Chmurzynska A. FADS1 and FADS2 polymorphism are associated with changes in fatty acid concentrations after calorie-restricted Central European and Mediterranean diets. Article. Menopause. Dec 2019;26(12):1415–1424. doi:10.1097/GME.0000000000001409 31567872 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
805 | Nabuco HCG, Tomeleri CM, Fernandes RR, Effects of Protein Intake Beyond Habitual Intakes Associated With Resistance Training on Metabolic Syndrome-Related Parameters, Isokinetic Strength, and Body Composition in Older Women. Journal: Article. J Aging PhysAct. Aug 1 2019;27(4):545–552. doi:10.1123/japa.2018-0370 | Intervention or Exposure
806 | Nadjarzadeh A, Ghadiri-Anari A, Ramezani-Jolfaie N, Effect of hypocaloric high-protein, low-carbohydrate diet supplemented with fennel on androgenic and anthropometric indices in overweight and obese women with polycystic ovary syndrome: A randomized placebo-controlled trial. Article. Complement Ther Med. Jan 2021;56:102633. doi: 10.1016/j.ctim.2020.102633 33271298 | Intervention or Exposure - Foods/Beverages Not Reported; Duration of Intervention
807 | Nagel EM, Jacobs D, Johnson KE, Maternal Dietary Intake of Total Fat, Saturated Fat, and Added Sugar Is Associated with Infant Adiposity and Weight Status at 6 mo of Age. J Nutr. Aug 7 2021;151(8):2353–2360. doi:10.1093/jn/nxab101 33982119 | Intervention or Exposure; Comparator
808 | Nakata Y, Sasai H, Gosho M, A Smartphone Healthcare Application, CALO mama Plus, to Promote Weight Loss: A Randomized Controlled Trial. Nutrients. Nov 2 2022;14(21)doi:10.3390/nu14214608 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
809 | Nakata Y, Sasai H, Tsujimoto T, Hashimoto K, Kobayashi H. A Single Motivational Lecture Can Promote Modest Weight Loss: a Randomized Controlled Trial. Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Obesity facts. 2020;13(2):267–278.32289804 | Intervention or Exposure
810 | Nansel TR, Cummings JR, Burger K, Siega-Riz AM, Lipsky LM. Greater Ultra-Processed Food Intake during Pregnancy and Postpartum Is Associated with Multiple Aspects of Lower Diet Quality. Article. Nutrients. Sep 22 2022;14(19)doi:10.3390/nu14193933 | Outcome
811 | Napier C, Warriner K, Sibiya MN, Reddy P. Nutritional status and dietary diversity of pregnant women in rural KwaZulu-Natal, South Africa. Health SA. 2019;24:1114. doi:10.4102/hsag.v24i0.1114 31934418 | Outcome
812 | Nasreddine L, Ayoub J, Abbas N, Abdul Malik M, Naja F. Postpartum Weight Retention and Its Determinants in Lebanon and Qatar: Results of the Mother and Infant Nutrition Assessment (MINA) Cohort. Int J Environ Res Public Health. Oct 27 2020;17(21 )doi:10.3390/ijerph17217851 | Intervention or Exposure
813 | Natale RA, Atem F, Weerakoon S, An Implementation Approach Comparison of a Child Care Center-Based Obesity Prevention Program. J Dev Behav Pediatr. Feb-Mar 01 2021;42(2):135–145. doi:10.1097/DBP.0000000000000861 32947578 | Intervention or Exposure
814 | Navarro-Martinez R, Mafla-Espana MA, Cauli O. Mediterranean Diet Adherence in Community-Dwelling Older Adults in Spain: Social Determinants Related to the Family. Nutrients. Dec 2 2022;14(23)doi:10.3390/nu14235141 | Study design
815 | Navas-Carretero S, San-Cristobal R, Livingstone KM, Higher vegetable protein consumption, assessed by an isoenergetic macronutrient exchange model, is associated with a lower presence of overweight and obesity in the web-based Food4me European study. Journal Article; Randomized Controlled Trial. International journal of food sciences and nutrition. 2019;70(2):240–253. | Study design; Intervention or Exposure
816 | Nestares T, Martin-Masot R, de Teresa C, Influence of Mediterranean Diet Adherence and Physical Activity on Bone Health in Celiac Children on a Gluten-Free Diet. Nutrients. May 13 2021;13(5)doi:10.3390/nu13051636 | Study design
817 | Neta A, Steluti J, Ferreira F, Farias Junior JC, Marchioni DML. Dietary patterns among adolescents and associated factors: longitudinal study on sedentary behavior, physical activity, diet and adolescent health. Article. Cien Saude Colet. 2021;26(suppl 2):3839–3851. Padroes alimentares de adolescentes e fatores associados: estudo longitudinal sobre comportamento sedentario, atividade fisica, alimentacao e saude dos adolescentes. doi:10.1590/1413-81232021269.2.24922019 | Study design
818 | Neuhouser ML, Pettinger M, Tinker LF, Associations of Biomarker-Calibrated Healthy Eating Index-2010 Scores with Chronic Disease Risk and Their Dependency on Energy Intake and Body Mass Index in Postmenopausal Women. J Nutr. Jan 14 2023;152(12):2808–2817. doi:10.1093/jn/nxac199 36040344 | Outcome
819 | Neves AM, Madruga SW. Complementary feeding, consumption of industrialized foods and nutritional status of children under 3 years old in Pelotas, Rio Grande do Sul, Brazil, 2016: a descriptive study. Article. Epidemiologia e servicos de saude: revista do Sistema Unico de Saude do Brasil. 2019;28(1):e2017507.30970067 | Study design
820 | Nezami B, Power J, Hurley L, Tate D. A randomized controlled trial of two diet monitoring approaches in a mobile weight loss intervention. Journal: Conference Abstract. Obesity (Silver Spring, Md). 2020;28(SUPPL 2):43-. | Intervention or Exposure; Publication status
821 | Ng AK, Hairi NN, Dahlui M, Su TT, Jalaludin MY, Abdul Majid H. The longitudinal relationship between dietary intake, physical activity and muscle strength among adolescents. Article. British Journal of Nutrition. 2020;124(11): 1207–1218.32624008 | Intervention or Exposure - Foods/Beverages Not Reported
822 | Nicholl A, Deering KE, Evelegh K, Whole-fat dairy products do not adversely affect adiposity or cardiometabolic risk factors in children in the Milky Way Study: a double-blind randomized controlled pilot study. American Journal of Clinical Nutrition. 2021;114(6):2025–2042.34633422 | Intervention or Exposure - Foods/Beverages Not Reported
823 | Nieczuja-Dwojacka J, Klemarczyk W, Siniarska A, Koziel S, Szysz T. Socio-economic determinants of the somatic development and reaction time of vegetarian and non-vegetarian children. Anthropol Anz. Apr 30 2020;77(2):137–146. doi: 10.1127/anthranz/2020/1107 32080703 | Study design; Intervention or Exposure
824 | Nikniaz L, Mahmudiono T, Jasim SA, Vajdi M, Thangavelu L, Farhangi MA. Nutrient pattern analysis of mineral based, simple sugar based, and fat based diets and risk of metabolic syndrome: a comparative nutrient panel. BMC Endocr Disord. Mar 2 2022;22(1):51. doi: 10.1186/s12902-022-00963-2 35232417 | Study design
825 | Njike VY, Treu JA, Kela GCM, Ayettey RG, Comerford BP, Siddiqui WT. Egg Consumption in the Context of Plant-Based Diets and Cardiometabolic Risk Factors in Adults at Risk of Type 2 Diabetes. Article in Press. J Nutr. Dec 3 2021;151(12):3651–3660. doi: 10.1093/jn/nxab283 34494112 | Duration of Intervention
826 | Noakes TD. Hiding unhealthy heart outcomes in a low-fat diet trial: The Women's Health Initiative Randomized Controlled Dietary Modification Trial finds that postmenopausal women with established coronary heart disease were at increased risk of an adverse outcome if they consumed a low-fat heart-healthy' diet. Article. Open Heart. 2021;8(2) | Study design; Health Status- 100% CVD
827 | Noerman S, Kokla M, Koistinen VM, Associations of the serum metabolite profile with a healthy Nordic diet and risk of coronary artery disease. Clin Nutr. May 2021;40(5):3250–3262. doi:10.1016/j.clnu.2020.10.051 33190988 | Intervention or Exposure; Outcome
828 | Noori S, Mirzababaei A, Abaj F, Ghaffarian-Ensaf R, Mirzaei K. Does the Mediterranean diet reduce the odds of diabetic nephropathy in women? A case-control study. Front Nutr. 2022;9:984622. doi:10.3389/fnut.2022.984622 36118745 | Study design; Health Status- 100% Diabetes; Outcome
829 | Nouri F, Sadeghi M, Mohammadifard N, Roohafza H, Feizi A, Sarrafzadegan N. Longitudinal association between an overall diet quality index and latent profiles of cardiovascular risk factors: results from a population based 13-year follow up cohort study. Nutr Metab (Lond). Mar 10 2021;18(1):28. doi: 10.1186/s12986-021-00560-5 33691729 | Intervention or Exposure; Outcome
830 | Nucci D, Arcidiacono D, Zaramella A, A MULTIMODAL APPROACH TO IMPROVE, BODY COMPOSITION, LIFESTYLE AND DIETARY BEHAVIORS IN BARRETT'S ESOPHAGUS PATIENTS: PRELIMINARY RESULTS OF A RANDOMIZED CONTROLLED TRIAL. Journal: Conference Abstract. Digestive and liver disease. 2020;52:S84–S85. | Health Status
831 | O'Brien EC, Geraghty AA, O'Sullivan EJ, Five-year follow up of a low glycaemic index dietary randomised controlled trial in pregnancy-no long-term maternal effects of a dietary intervention. Article. BJOG. Mar 2019;126(4):514–524. doi: 10.1111/1471-0528.15500 30303614 | Intervention or Exposure - Foods/Beverages Not Reported; Data overlap
832 | Odegaard AO, Jacobs DR, Van Wagner LB, Pereira MA. Levels of abdominal adipose tissue and metabolic-associated fatty liver disease (MAFLD) in middle age according to average fast-food intake over the preceding 25 years: the CARDIA Study. Am J Clin Nutr. Jul 6 2022;116(1):255–262. doi:10.1093/ajcn/nqac079 35679431 | Intervention or Exposure
833 | Ofir N, Mizrakli Y, Greenshpan Y, Vertebrae but not femur marrow fat transiently decreases in response to body weight loss in an 18-month randomized control trial. Article. Bone. Jun 2023;171:116727. doi:10.1016/j.bone.2023.116727 36898571 | Intervention or Exposure - Foods/Beverages Not Reported
834 | Ogilvie A, Schlussel Y, Schneider S, Shapses S. Higher diet quality score increases weight loss during moderate caloric restriction with no greater loss of bone mineral density. Journal: Conference Abstract. Journal of bone and mineral research. 2020;35(SUPPL 1): 126-. | Intervention or Exposure; Outcome; Comparator
835 | Ogilvie AR, Schlussel Y, Sukumar D, Meng L, Shapses SA. Higher protein intake during caloric restriction improves diet quality and attenuates loss of lean body mass. Obesity (Silver Spring). Jul 2022;30(7):1411–1419. doi:10.1002/oby.23428 35538903 | Publication status
836 | Oh CM, Kim Y, Yang J, Choi S, Oh K. Changes in health behaviors and obesity of Korean adolescents before and during the COVID-19 pandemic: a special report using the Korea Youth Risk Behavior Survey. Epidemiology and Health. Feb 14 2023;45 doi:ARTN e2023018 | Study design; Intervention or Exposure
837 | Oh J, Oda K, Dang K, Ibrayev Y, Fraser GE, Knutsen SF. Lower Compliance with Cervical Cancer Screening Guidelines Among Vegetarians in North America. J Prev. Dec 2022;43(6):783–800. doi:10.1007/s10935-022-00691-2 | Outcome
838 | O'Hearn M, Erndt-Marino J, Gerber S, Validation of Food Compass with a healthy diet, cardiometabolic health, and mortality among U.S. adults, 1999–2018. Nat Commun. Nov 22 2022;13(1):7066. doi:10.1038/s41467-022-34195-8 36414619 | Study design
839 | Ohman EA, Kirchner L, Winkvist A, Effects of dietary and exercise treatments on HDL subclasses in lactating women with overweight and obesity: a secondary analysis of a randomised controlled trial. Article. Br J Nutr. Dec 14 2022;128(11):2105–2114. doi: 10.1017/S0007114522000241 35067237 | Outcome
840 | Ojeda Rodriguez A, Zazpe I, Morell Azanza L, Chueca M, Azcona Sanjulian M, Marti A. Improved vitamin D adequacy and its associations with diet quality indices in a lifestyle intervention of children and adolescents with abdominal obesity. Journal: Conference Abstract. Obesity facts. 2019;12:112-. | Publication status
841 | Ojeda-Rodriguez A, Morell-Azanza L, Zalba G, Zazpe I, Azcona-Sanjulian MC, Marti A. Associations of telomere length with two dietary quality indices after a lifestyle intervention in children with abdominal obesity: a randomized controlled trial. Pediatr Obes. Nov 2020;15(11):e12661. doi: 10.1111/ijpo.12661 32558330 | Outcome; Comparator
842 | Okazaki K, Ohira T, Sakai A, Lifestyle Factors Associated with Undernutrition in Older People after the Great East Japan Earthquake: A Prospective Study in the Fukushima Health Management Survey. Article. Int J Environ Res Public Health. Mar 14 2022;19(6)doi:10.3390/ijerph19063399 | Intervention or Exposure
843 | Okubo H, Nakayama SF, Grp JECsS. Periconceptional maternal diet quality influences blood heavy metal concentrations and their effect on low birth weight: the Japan Environment and Children's Study. Environ Int. Mar 2023;173 doi:ARTN 107808 | Outcome
844 | Olfert MD, Barr ML, Mathews AE, Life of a vegetarian college student: Health, lifestyle, and environmental perceptions. J Am Coll Health. Jan 2022;70(1):232–239. doi:10.1080/07448481.2020.1740231 32343196 | Intervention or Exposure
845 | Olifa N, Moesiyanti YES, Purba A. Integrated nutrition interventions reduce metabolic syndrome: study of integrated interventions by diet, behavior, physical activity on overweight in junior high school children in bandung city. Conference Abstract. Annals of Nutrition & Metabolism. 2019;75(3):388 | Study design; Intervention or Exposure; Comparator
846 | Oliver TL, Shenkman R, Diewald LK, A Year in the Life of U.S. Frontline Health Care Workers: Impact of COVID-19 on Weight Change, Physical Activity, Lifestyle Habits, and Psychological Factors. Nutrients. Nov 17 2022;14(22)doi:10.3390/nu14224865 | Intervention or Exposure
847 | Oliverio A, Radice P, Colombo M, The Impact of Mediterranean Dietary Intervention on Metabolic and Hormonal Parameters According to BRCA1/2 Variant Type. Front Genet. 2022;13:820878. doi:10.3389/fgene.2022.820878 35356420 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
848 | Olmedo-Requena R, Martinez-Galiano JM, Amezcua-Prieto C, Association between low dairy intake during pregnancy and small for gestational age infants. Eur J Clin Nutr. Dec 2019;73(12):1642–1645. doi:10.1038/s41430-019-0513-y 31611637 | Intervention or Exposure
849 | Ooi DSQ, Toh JY, Bin Ng LY, Dietary Intakes and Eating Behavior between Metabolically Healthy and Unhealthy Obesity Phenotypes in Asian Children and Adolescents. Nutrients. Nov 2022;14(22)doi:ARTN 4796 | Study design; Intervention or Exposure
850 | Ooi EM, Lichtenstein AH, Millar JS, Effects of Therapeutic Lifestyle Change diets high and low in dietary fish-derived FAs on lipoprotein metabolism in middle-aged and elderly subjects. Article. J Lipid Res. Sep 2012;53(9):1958–67. doi:10.1194/jlr.P024315 22773687 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
851 | Ortner Hadziabdic M, Mucalo I, Hrabac P, Matic T, Rahelic D, Bozikov V. Factors predictive of drop-out and weight loss success in weight management of obese patients. Academic Journal. Journal of human nutrition and dietetics. 2015;28:24–32.25220046 | Intervention or Exposure - Foods/Beverages Not Reported
852 | Osorio-Conles O, Olbeyra R, Moize V, Effect of a short-term mediterranean diet supplemented with almonds on adipose tissue function. Journal: Conference Abstract. Obesity (Silver Spring, Md). 2020;28(SUPPL 2):83–84. | Publication status
853 | Osorio-Conles O, Olbeyra R, Moize V, Positive Effects of a Mediterranean Diet Supplemented with Almonds on Female Adipose Tissue Biology in Severe Obesity. Article. Nutrients. Jun 24 2022;14(13)doi:10.3390/nu14132617 | Intervention or Exposure; Outcome
854 | Otsuka R, Zhang S, Tange C, Association of Dietary Intake with the Transitions of Frailty among JapaneseCommunity-Dwellinc Older Adults. Article. J Frailty Aging. 2022;11(1):26–32. doi:10.14283/jfa.2021.42 35122087 | Intervention or Exposure; Outcome
855 | Ovaska Effects of Western Style or Mediterranean Diet on Insulin Resistance Markers in Female BRCA1/2 Mutation Carriers (Libre Study). Journal: Conference Abstract. Clinical nutrition (Edinburgh, Scotland). 2019;38:S99–S100. | Publication status
856 | Ovcharova E, Danovska M, Marinova D, Adapted Mediterranean Diet Impact on the Symptoms of Chronic Fatigue, Serum Levels of Omega-3 Polyunsaturated Fatty Acids (Pufas) and Interleukin 17 (11–17) in Patients with Relapsing-Remitting Multiple Sclerosis Undergoing Disease-Modifying Therapy: A Pilot Study. Article. Journal of IMAB - Annual Proceeding (Scientific Papers). 2022;28(1):4297–4304. doi:10.5272/jimab.2022281.4297 | Health Status
857 | Ozrail M, Alardawi A, Reeder N, Mosby T. Body Fat Distribution (Android vs. Gynoid) and Dietary Intake Among Young Women Enrolled at Mississippi State University. Journal of the Academy of | Publication status
858 | Pacyga DC, Talge NM, Gardiner JC, Calafat AM, Schantz SL, Strakovsky RS. Maternal diet quality moderates associations between parabens and birth outcomes. Environ Res. Nov 2022;214(Pt 3):114078. doi:10.1016/j.envres.2022.114078 35964672 | Intervention or Exposure; Outcome
859 | Pagano R, Torreglosa CR, Dantas de Oliveira J, Effects of a cardioprotective nutritional program (BALANCE program) on diet quality, anthropometric features and cardiovascular risk factors in primary cardiovascular prevention: A workplace feasibility study. Article. Human Nutrition & Metabolism. 2022;30doi:10.1016/j.hnm.2022.200161 | Study design; Comparator
860 | Pagliai G, Russo E, Baldi S, Impact of mediterranean vs vegetarian diets on gut microbiota and short chain fatty acids: the CARDIVEG study. Journal: Conference Abstract. Nutrition, metabolism and cardiovascular diseases. 2019;29(8):879-. | Publication status
861 | Pagliai G, Russo E, Niccolai E, Influence of a 3-month low-calorie Mediterranean diet compared to the vegetarian diet on human gut microbiota and SCFA: the CARDIVEG Study. Eur J Nutr. Aug 2020;59(5):2011–2024. doi:10.1007/s00394-019-02050-0 31292752 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
862 | Pagliai G, Russo E, Niccolai E, Influence of a 3-months low-calorie Mediterranean diet vs. Vegetarian diet on human gut microbiota and SCFA: the CARDIVEG Study. Journal: Conference Abstract. Proceedings of the Nutrition Society. 2020;79(OCE2) | Publication status
863 | Pajunen L, Korkalo L, Koivuniemi E, A healthy dietary pattern with a low inflammatory potential reduces the risk of gestational diabetes mellitus. Eur J Nutr. Apr 2022;61(3):1477–1490. doi:10.1007/s00394-021-02749-z 34846602 | Outcome
864 | Palau-Rodriguez M, Garcia-Aloy M, Minarro A, Effects of a long-term lifestyle intervention on metabolically healthy women with obesity: Metabolite profiles according to weight loss response. Clin Nutr. Jan 2020;39(1):215–224. doi:10.1016/j.clnu.2019.01.018 30862367 | Intervention or Exposure; Outcome; Comparator
865 | Palkowska-Gozdzik E, Piotrowicz K, Krzesinski P, Stanczyk A, Skrobowski A, Gielerak G. Crosstalk Between Dietary Pattern, Anthropometric Parameters, and Adiponectin Concentration Among Patients with Metabolic Syndrome. Metab Syndr Relat Disord. Apr 2021;19(3):137–143. doi: 10.1089/met.2020.0058 33170092 | Study design; Intervention or Exposure; Comparator
866 | Palnati M, Marcus BH, Pekow P, Rosal MC, Manson JE, Chasan-Taber L. The Impact of a Lifestyle Intervention on Postpartum Weight Retention Among At-Risk Hispanic Women. Article. Am J Prev Med. Jul 2021;61(1):44–54. doi:10.1016/j.amepre.2021.02.005 33994252 | Intervention or Exposure
867 | Pan F, Wang Z, Wang H, Association between Ultra-Processed Food Consumption and Metabolic Syndrome among Adults in China-Results from the China Health and Nutrition Survey. Nutrients. Feb 2 2023;15(3)doi:10.3390/nu15030752 | Intervention or Exposure - Foods/Beverages Not Reported; Country
868 | Pan L, Shi K, Lv J, Association of dietary patterns, circulating lipid profile, and risk of obesity. Obesity (Silver Spring). May 2023;31(5):1445–1454. doi:10.1002/oby.23720 37037666 | Study design; Country
869 | Pan XF, Magliano DJ, Zheng M, Seventeen-Year Associations between Diet Quality Defined by the Health Star Rating and Mortality in Australians: The Australian Diabetes, Obesity and Lifestyle Study (AusDiab). Curr Dev Nutr. Nov 2020;4(11):nzaa157. doi: 10.1093/cdn/nzaa157 33204933 | Outcome
870 | Pandya R, Abdelaal R, Chen JW, Retrospective assessment of metabolic syndrome components in early adult life on vegetarian dietary status. Front Public Health. 2022;10:945805. doi: 10.3389/fpubh.2022.945805 36052004 | Intervention or Exposure - Foods/Beverages Not Reported
871 | Pang T, Alman AC, Gray HL, Basu A, Shi L, Snell-Bergeon JK. Empirical dietary inflammatory pattern and metabolic syndrome: prospective association in participants with and without type 1 diabetes mellitus in the coronary artery calcification in type 1 diabetes (CACTI) study. Article. Nutr Res. Oct 2021;94:1–9. doi: 10.1016/j.nutres.2021.08.001 34571214 | Size or Power
872 | Panizza CE, Lim U, Yonemori KM, Effects of Intermittent Energy Restriction Combined with a Mediterranean Diet on Reducing Visceral Adiposity: A Randomized Active Comparator Pilot Study. Journal Article; Randomized Controlled Trial. Nutrients. Jun 20 2019;11(6)doi:10.3390/nu11061386 | Duration of Intervention; Comparator
873 | Pannen ST, Maldonado SG, Nonnenmacher T, Adherence and Dietary Composition during Intermittent vs. Continuous Calorie Restriction: Follow-Up Data from a Randomized Controlled Trial in Adults with Overweight or Obesity. Nutrients. Apr 5 2021;13(4)doi:10.3390/nu13041195 | Intervention or Exposure
874 | Papada E, Amerikanou C, Forbes A, Kaliora AC. Adherence to Mediterranean diet in Crohn's disease. Eur J Nutr. Apr 2020;59(3):1115–1121. doi:10.1007/s00394-019-01972-z 31006053 | Study design; Outcome
875 | Papandreou P, Amerikanou C, Vezou C, Gioxari A, Kaliora AC, Skouroliakou M. Improving Adherence to the Mediterranean Diet in Early Pregnancy Using a Clinical Decision Support System; A Randomised Controlled Clinical Trial. Nutrients. Jan 14 2023;15(2)doi: 10.3390/nu15020432 | Outcome
876 | Papandreou P, Gioxari A, Daskalou E, Grammatikopoulou MG, Skouroliakou M, Bogdanos DP. Mediterranean Diet and Physical Activity Nudges versus Usual Care in Women with Rheumatoid Arthritis: Results from the MADEIRA Randomized Controlled Trial. Nutrients. Jan 28 2023;15(3)doi:10.3390/nu15030676 | Health Status; Comparator
877 | Papazian T, Salameh P, Abi Tayeh G, Dietary patterns and birth outcomes of healthy Lebanese pregnant women. Front Nutr. 2022;9:977288. doi: 10.3389/fnut.2022.977288 36238451 | Did not account for at least 1 key confounder
878 | Papazian T, Serhal A, Hout H, Discrepancies among different tools evaluating Mediterranean diet adherence during pregnancy, correlated to maternal anthropometric, dietary and biochemical characteristics. Article. Clinical Nutrition. 2019;38(3):1398–1405.30394287 | Did not account for at least 1 key confounder
879 | Papier K, Appleby PN, Fensom GK, Vegetarian diets and risk of hospitalisation or death with diabetes in British adults: results from the EPIC-Oxford study. Article. Nutr Diabetes. Feb 25 2019;9(1):7. doi:10.1038/s41387-019-0074-0 30804320 | Outcome
880 | Park E, Ko Y. Trends in Obesity and Obesity-Related Risk Factors among Adolescents in Korea from 2009 to 2019. Article. Int J Environ Res Public Health. May 6 2022;19(9)doi:10.3390/ijerph19095672 | Study design; Intervention or Exposure
881 | Park S. A Causal and Inverse Relationship between Plant-Based Diet Intake and in a Two-Sample Mendelian Randomization Study. Foods. Jan 26 2023;12(3)doi:10.3390/foods12030545 | Study design
882 | Park S. Association of polygenic risk scores for insulin resistance risk and their interaction with a plant-based diet, especially fruits, vitamin C, and flavonoid intake, in Asian adults. Nutrition. Jul 2023;111 doi:ARTN 112007 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
883 | Park S. Interaction of Polygenetic Variants for Gestational Diabetes Mellitus Risk with Breastfeeding and Korean Balanced Diet to Influence Type 2 Diabetes Risk in Later Life in a Large Hospital-Based Cohort. J Pers Med. Nov 10 2021;11(11)doi:10.3390/jpm11111175 | Study design; Outcome
884 | Park SY, Love P, Lacy KE, Campbell KJ, Zheng M. Describing the longitudinal breakfast quality index trajectories in early childhood: results from Melbourne InFANT program. Eur J Clin Nutr. Mar 2023;77(3):363–369. doi:10.1038/s41430-022-01249-5 36494475 | Intervention or Exposure
885 | Park SY, Shvetsov YB, Kang M, Changes in Diet Quality over 10 Years Are Associated with Baseline Sociodemographic and Lifestyle Factors in the Multiethnic Cohort Study. J Nutr. Jul 1 2020;150(7):1880–1888. doi:10.1093/jn/nxaa102 32338763 | Outcome
886 | Parker EA, Perez WJ, Phipps B, Dietary Quality and Perceived Barriers to Weight Loss among Older Overweight Veterans w Dysmobility. International Journal of Environmental Research and Public Health. Aug 2022;19(15)doi:ARTN 9153 | Study design
887 | Parker HW, Tovar A, McCurdy K, Vadiveloo M. Associations between pre-pregnancy BMI, gestational weight gain, and prenatal diet quality in a national sample. Article. PLoS ONE. 2019;14(10) | Data overlap
888 | Parker SM, Barr M, Stocks N, Preventing chronic disease in overweight and obese patients with low health literacy using eHealth and teamwork in primary healthcare (HeLP-GP): a cluster randomised controlled trial. BMJ Open. Nov 30 2022;12(11):e060393. doi:10.1136/bmjopen-2021-060393 | Intervention or Exposure
889 | Parnell LD, Noel SE, Bhupathiraju SN, Metabolite patterns link diet, obesity, and type 2 diabetes in a Hispanic population. Metabolomics. Sep 22 2021;17(10):88. doi:10.1007/s11306-021-01835-x 34553271 | Intervention or Exposure - Foods/Beverages Not Reported
890 | Parra-Fernandez ML, Manzaneque-Canadillas M, Onieva-Zafra MD, Pathological Preoccupation with Healthy Eating (Orthorexia Nervosa) in a Spanish Sample with Vegetarian, Vegan, and Non-Vegetarian Dietary Patterns. Nutrients. Dec 21 2020;12(12)doi:10.3390/nu12123907 | Study design; Outcome
891 | Pascual RW, Phelan S, La Frano MR, Pilolla KD, Griffiths Z, Foster GD. Diet Quality and Micronutrient Intake among Long-Term Weight Loss Maintainers. Nutrients. Dec 13 2019;11(12)doi:10.3390/nu11123046 | Study design; Outcome
892 | Pattar S, Shetty P, Shetty GB. Impact of vegetarian versus non-vegetarian diet on health outcomes in male individuals: A comparative study. Article in Press. Advances in Integrative Medicine. 2023;10(1):1–7. doi: 10.1016/j.aimed.2023.02.001 | Intervention or Exposure; Country
893 | Pattinson AL, Seimon RV, Harper C, Diet Quality following Total Meal Replacement Compared with Food-Based Weight-Loss Diets in Postmenopausal Women with Obesity: A Secondary Analysis of the TEMPO Diet Triall. 2021;doi:10.1093/jn/nxab311 | Comparator
894 | Pauley M, Mays C, Bailes JR, Jr., Carbohydrate-Restricted Diet: A Successful Strategy for Short-Term Management in Youth with Severe Obesity-An Observational Study. Article. Metab Syndr Relat Disord. Jun 2021;19(5):281–287. doi: 10.1089/met.2020.0078 33566732 | Study design; Intervention or Exposure
895 | Pawlak R, Judd N, Donati GL, Perrin MT. Prevalence and Predictors of Low Breast Milk Iodine Concentration in Women Following Vegan, Vegetarian, and Omnivore Diets. Article. Breastfeed Med. Jan 2023;18(1):37–42. doi:10.1089/bfm.2022.0211 36450113 | Study design; Outcome
896 | Peacock L, Seed PT, Dalrymple KV, White SL, Poston L, Flynn AC. The UK Pregnancies Better Eating and Activity Trial (UPBEAT); Pregnancy Outcomes and Health Behaviours by Obesity Class. Int J Environ Res Public Health. Jun 30 2020;17(13)doi: 10.3390/ijerph17134712 | Intervention or Exposure - Foods/Beverages Not Reported
897 | Peila R, Lane DS, Shadyab AH, Healthy lifestyle index and the risk of ductal carcinoma in situ of the breast in the Women's Health Initiative. Int J Cancer. Aug 15 2022;151(4):526–538. doi: 10.1002/ijc.34034 35429338 | Outcome
898 | Pellonpera O, Koivuniemi E, Vahlberg T, Dietary quality influences body composition in overweight and obese pregnant women. Article. Clin Nutr. Aug 2019;38(4):1613–1619. doi:10.1016/j.clnu.2018.08.029 30224302 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
899 | Peng LN, Yu PC, Lee HF, Lin MH, Chen LK. Protein-enriched diet improved muscle endurance and marginally reduced intramuscular adiposity: results from a randomized controlled trial among middle-aged and older adults. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Archives of gerontology and geriatrics. 2021;96:104436.34098214 | Intervention or Exposure - Foods/Beverages Not Reported
900 | Pereira-da-Silva L, Virella D. Which type of maternal dietary polyunsaturated fat affects fetal adiposity?...Kennedy RAK, Mullaney L, O’Higgins AC The relationship between early pregnancy dietary intakes and subsequent birthweight and neonatal adiposity. Journal of Public Health, Dec 2018; 40(4):747–755. 2020;42:639–639.30590769 | Publication status
901 | Perera MJ, Chirinos DA, Brintz CE, Body Mass of U.S. Hispanics/Latinos From the Hispanic Community Health Study/Study of Latinos (HCHS/SOL): How Do Diet Quality and Sedentary Time Relate? 2020; 18(2)doi: 10.1177/1540415319874809 | Study design
902 | Perez-Rodrigo C, Hervas Barbara G, Gianzo Citores M, Aranceta-Bartrina J. Prevalence of obesity and associated cardiovascular risk factors in the Spanish population: the ENPE study. Rev Esp Cardiol (Engl Ed). Mar 2022;75(3):232–241. doi:10.1016/j.rec.2020.12.020 33773941 | Study design
903 | Perng W, Harte R, Ringham BM, A Prudent dietary pattern is inversely associated with liver fat content among multi-ethnic youth. Pediatr Obes. Jun 2021;16(6):e12758. doi:10.1111/ijpo.12758 33296951 | Outcome
904 | Perry CA, Van Guilder GP, Butterick TA. Decreased myostatin in response to a controlled DASH diet is associated with improved body composition and cardiometabolic biomarkers in older adults: results from a controlled-feeding diet intervention study. 2022;8(1)doi:10.1186/s40795-022-00516-9 | Study design; Intervention or Exposure
905 | Perry CA, Van Guilder GP, Hossain M, Kauffman A. Cardiometabolic Changes in Response to a Calorie-Restricted DASH Diet in Obese Older Adults. Front Nutr. 2021;8:647847. doi:10.3389/fnut.2021.647847 33816541 | Study design; Intervention or Exposure; Data overlap
906 | Perry CA, Van Guilder GP, Kauffman A, Hossain M. A Calorie-Restricted DASH Diet Reduces Body Fat and Maintains Muscle Strength in Obese Older Adults. Nutrients. Dec 30 2019;12(1)doi:10.3390/nu12010102 | Study design
907 | Perry CD, Degeneffe D, Davey C, Kollannoor-Samuel G, Reicks M. Weight Gain Prevention among Midlife Women: A Randomized Controlled Trial to Address Needs Related to the Physical and Social Environment. Article. Int J Environ Res Public Health. May 25 2016; 13(6)doi:10.3390/ijerph13060530 | Intervention or Exposure
908 | Perticone M, Maio R, Sciacqua A, Ketogenic Diet-Induced Weight Loss is Associated with an Increase in Vitamin D Levels in Obese Adults. Article. Molecules (Basel, Switzerland). 2019;24(13) | Intervention or Exposure - Foods/Beverages Not Reported
909 | Petermann-Rocha F, Celis-Morales C, Pell JP, Ho FK. Do all vegetarians have a lower cardiovascular risk? A prospective study. Article. Clin Nutr. Mar 2023;42(3):269–276. doi: 10.1016/j.clnu.2023.01.010 36716619 | Outcome
910 | Petermann-Rocha F, Ho FK, Foster H, Nonlinear Associations Between Cumulative Dietary Risk Factors and Cardiovascular Diseases, Cancer, and All-Cause Mortality: A Prospective Cohort Study From UK Biobank. Article. Mayo Clin Proc. Sep 2021;96(9):2418–2431. doi:10.1016/j.mayocp.2021.01.036 34366141 | Outcome; Publication status
911 | Petermann-Rocha F, Parra-Soto S, Gray S, Vegetarians, fish, poultry, and meat-eaters: who has higher risk of cardiovascular disease incidence and mortality? A prospective study from UK Biobank. Article. Eur Heart J. Mar 21 2021;42(12):1136–1143. doi: 10.1093/eurheartj/ehaa939 33313747 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
912 | Petersen KS, Murphy J, Whitbread J, Clifton PM, Keogh JB. The Effect of a Peanut-Enriched Weight Loss Diet Compared to a Low-Fat Weight Loss Diet on Body Weight, Blood Pressure, and Glycemic Control: A Randomized Controlled Trial. Nutrients. Jul 21 2022;14(14)doi:10.3390/nu14142986 | Intervention or Exposure - Foods/Beverages Not Reported
913 | Petry CJ, Ong KK, Hughes IA, Acerini CL, Dunger DB. Temporal Trends in Maternal Food Intake Frequencies and Associations with Gestational Diabetes: The Cambridge Baby Growth Study. Nutrients. Nov 19 2019;11(11):2822. doi:10.3390/nu11112822 31752255 | Outcome
914 | Phelan S, Halfman T, Pinto AM, Foster GD. Behavioral and Psychological Strategies of Long-Term Weight Loss Maintainers in a Widely Available Weight Management Program. Obesity (Silver Spring). Feb 2020;28(2):421–428. doi:10.1002/oby.22685 31970912 | Study design; Intervention or Exposure
915 | Phuong NM, Giang NH, Linh NT, Hien VTT, Huong LT, Yamamoto S. Effects of High-Protein and High-Carbohydrate Diets on Body Weight Were Similar in Healthy Young Vietnamese Women With Normal Body Weight. Nutrition Today. 2019;54(6):271–276. | Duration of Intervention
916 | Pickering RT, Bradlee ML, Singer MR, Moore LL. Baseline diet modifies the effects of dietary change. Br J Nutr. Apr 28 2020;123(8):951–958. doi:10.1017/S0007114520000112 31959264 | Intervention or Exposure
917 | Pinto A, Santos AC, Lopes C, Oliveira A. Dietary patterns at 7 year-old and their association with cardiometabolic health at 10 year-old. Clin Nutr. Apr 2020;39(4):1195–1202. doi:10.1016/j.clnu.2019.05.007 31133488 | Outcome
918 | Pinto X, Fanlo-Maresma M, Corbella E, A Mediterranean Diet Rich in Extra-Virgin Olive Oil Is Associated with a Reduced Prevalence of Nonalcoholic Fatty Liver Disease in Older Individuals at High Cardiovascular Risk. Article. J Nutr. Nov 1 2019;149(11):1920–1929. doi:10.1093/jn/nxz147 31334554 | Outcome
919 | Plante AS, Lemieux S, Drouin-Chartier JP, Changes in Eating Behaviours Throughout Pregnancy: Associations with Gestational Weight Gain and Pre-pregnancy Body Mass Index. Article. J Obstet Gynaecol Can. Jan 2020;42(1):54–60. doi: 10.1016/j.jogc.2019.04.024 31289011 | Intervention or Exposure
920 | Plante AS, Savard C, Lemieux S, Trimester-Specific Intuitive Eating in Association With Gestational Weight Gain and Diet Quality. Article. J Nutr Educ Behav. Jun 2019;51(6):677–683. doi: 10.1016/j.jneb.2019.01.011 30765299 | Intervention or Exposure; Comparator
921 | Pletsch-Borba L, Wernicke C, Apostolopoulou K, Nutritional counseling frequency and baseline food pattern predict implementation of a high-protein and high-polyunsaturated fatty acid dietary pattern: 1-year results of the randomized NutriAct trial. Clin Nutr. Nov 2021;40(11):5457–5466. doi:10.1016/j.clnu.2021.09.022 34656026 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
922 | Popp CJ, Hu L, Kharmats AY, Effect of a Personalized Diet to Reduce Postprandial Glycemic Response vs a Low-fat Diet on Weight Loss in Adults With Abnormal Glucose Metabolism and Obesity: A Randomized Clinical Trial. JAMA Netw Open. Sep 1 2022;5(9):e2233760. doi:10.1001/jamanetworkopen.2022.33760 36169954 | Intervention or Exposure
923 | Poracova J, Uher I, Vaskova H, Effectiveness of Adherence to a Mediterranean Diet in the Management of Overweight Women: The Prospective Interventional Cohort Study. Int J Environ Res Public Health. Nov 29 2022;19(23)doi: 10.3390/ijerph192315927 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
924 | Porter Starr KN, Connelly MA, Orenduff MC, Impact on cardiometabolic risk of a weight loss intervention with higher protein from lean red meat: Combined results of 2 randomized controlled trials in obese middle-aged and older adults. Article. J Clin Lipidol. Nov-Dec 2019;13(6):920–931. doi: 10.1016/j.jacl.2019.09.012 31771921 | Intervention or Exposure - Foods/Beverages Not Reported
925 | Poulimeneas D, Anastasiou CA, Santos I, Hill JO, Panagiotakos DB, Yannakoulia M. Exploring the relationship between the Mediterranean diet and weight loss maintenance: the MedWeight study. Br J Nutr. Oct 28 2020;124(8):874–880. doi: 10.1017/S0007114520001798 32436489 | Size or Power
926 | Poulimeneas D, Zoupi K, Mamalaki E, Higher adherence to the Mediterranean Diet is associated with weight loss maintenance: the MedWeight study. Proceedings of the Nutrition Society. 2020;79(OCE2):1–1.31985390 | Publication status
927 | Powell LM, Jones K, Duran AC, Tarlov E, Zenk SN. The price of ultra-processed foods and beverages and adult body weight: Evidence from U.S. veterans. Article. Econ Hum Biol. Aug 2019;34:39–48. doi:10.1016/j.ehb.2019.05.006 31204255 | Intervention or Exposure
928 | Prado G, Fernandez A, St George SM, Results of a Family-Based Intervention Promoting Healthy Weight Strategies in Overweight Hispanic Adolescents and Parents: An ROT. Am J Prev Med. Nov 2020;59(5):658–668. doi:10.1016/j.amepre.2020.06.010 33011010 | Intervention or Exposure
929 | Prapkree L, Uddin R, Jaafar JAA, Snacking behavior is associated with snack quality, overall diet quality, and body weight among US college students. Nutrition Research. Jun 2023;114:41–49. doi:10.1016/j.nutres.2023.04.005 37182440 | Study design
930 | Pretorius RA, Palmer DJ. High-Fiber Diet during Pregnancy Characterized by More Fruit and Vegetable Consumption. Nutrients. 2021;13(1):35–35. | Intervention or Exposure; Outcome
931 | Prieto-Zambrano P, Pache-lglesias L, Dominguez-Martin AT, Panea-Pizarro I, Gomez-Luque A, Lopez-Espuela F. Impact of an educational intervention on the quality of the Mediterranean diet, physical activity and weight status in adolescents: Randomised clinical trial. Enferm Clin (Engl Ed). Jan-Feb 2021;31(1):51–56. Impacto de una intervencion educacional sobre la calidad de la dieta mediterranea, la actividad fisica y el estado ponderal en adolescentes: ensayo clinico aleatorizado. doi:10.1016/j.enfcli.2020.03.003 32299659 | Intervention or Exposure; Outcome
932 | Primo D, Izaola O, de Luis D. Effects of a high protein/low carbohydrate low-calorie diet versus a standard low-calorie diet on anthropometric parameters and cardiovascular risk factors, role of polymorphism rs3123554 in the cannabinoid receptor gene type 2 (CB2R). Article. Endocrinol Diabetes Nutr (Engl Ed). Aug-Sep 2020;67(7):446–453. Efectos de una dieta hipocalorica rica en proteina/baja de hidratos de carbono vs. una estandar sobre los parametros antropometricos y factores de riesgo cardiovascular, papel del polimorfismo rs3123554 del gen del receptor canabinoide tipo 2 (CB2R). doi:10.1016/j.endinu.2019.09.010 31839571 | Intervention or Exposure - Foods/Beverages Not Reported
933 | Primo D, Izaola O, Lopez JJ, de Luis DA. Brain derived neurotrophic factor (BDNF) polymorphism rs 10767664 affects metabolic parameters after weight loss secondary to high fat hypocaloric diet with Mediterranean pattern. Article. Eur Rev Med Pharmacol Sci. Feb 2021;25(4):1944–1953. doi:10.26355/eurrev_202102_25094 33660804 | Study design; Comparator
934 | Primo Martin D, Izaola Jauregui O, Lopez Gomez JJ, [Effect of a Mediterranean-pattern diet on the metabolic response secondary to weight loss; role of the single nucleotide polymorphism (rs16147) of neuropeptide Y]. Journal Article; Randomized Controlled Trial. Nutr Hosp. Aug 27 2020;37(4):742–749. Efecto de una dieta de patron mediterraneo en la respuesta metabolica secundaria a la perdida de peso; papel del polimorfismo de un unico nucleotido (rs16147) del gen del neuropeptido Y. doi:10.20960/nh.02941 32686440 | Language
935 | Psota TL, Tindall AM, Lohse B, Miller PE, Petersen KS, Kris-Etherton PM. The Weight Optimization Revamping Lifestyle using the Dietary Guidelines (WORLD) Study: Sustained Weight Loss Over 12 Months. Obesity (Silver Spring). Jul 2020;28(7):1235–1244. doi: 10.1002/oby.22824 32475085 | Size or Power
936 | Ptomey LT, Montgomery RN, Gorczyca AM, The impact of exercise and cumulative physical activity on energy intake and diet quality in adults enrolled in the Midwest Exercise Trial for the Prevention of Weight Regain. Br J Nutr. Dec 28 2022;128(12):2498–2509. doi: 10.1017/S0007114521005122 35249561 | Study design; Intervention or Exposure
937 | Ptomey LT, Washburn RA, Goetz JR, A randomized trial comparing diet and delivery strategies for weight management in adolescents with intellectual disabilities. Article in Press. Pediatr Obes. Jan 2023;18(1):e12972. doi: 10.1111/ijpo.12972 36054481 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
938 | Purnamasari SD, Hsu CY, Chen YT, Kurniawan AL, Lee HA, Chao JC. Combined Low Plant and High Animal Dietary Pattern Is Associated with a Lower Risk of Anemia among Dyslipidemic Adult Women in Taiwan: A Retrospective Study from 2001 to 2015. Article. Int J Environ Res Public Health. May 20 2022;19(10)doi: 10.3390/ijerph19106231 | Study design; Comparator
939 | Qin R, Ding Y, Lu Q, Associations of maternal dietary patterns during pregnancy and fetal intrauterine development. Front Nutr. 2022;9:985665. doi:10.3389/fnut.2022.985665 36185689 | Outcome
940 | Qin Y, Chen Y, Zhang Z, Associations of dietary inflammatory potential with postpartum weight change and retention: Results from a cohort study. Obesity (Silver Spring). Oct 2021;29(10):1689–1699. doi:10.1002/oby.23238 34490743 | Intervention or Exposure - Foods/Beverages Not Reported
941 | Quansah DY, Schenk S, Gilbert L, Intuitive Eating Behavior, Diet Quality and Metabolic Health in the Postpartum in Women with Gestational Diabetes. Nutrients. Oct 13 2022;14(20)doi:10.3390/nu14204272 | Intervention or Exposure; Comparator
942 | Quetglas-Llabres MM, Monserrat-Mesquida M, Bouzas C, Inflammatory and Oxidative Stress Markers Related to Adherence to the Mediterranean Diet in Patients with Metabolic Syndrome. Antioxidants (Basel). May 1 2022;11(5)doi:10.3390/antiox11050901 | Study design
943 | Quillen EE, Beavers DP, O'Brien Cox A, Use of Metabolomic Profiling to Understand Variability in Adiposity Changes Following an Intentional Weight Loss Intervention in Older Adults. Nutrients. Oct 19 2020;12(10):3188. doi:10.3390/nu12103188 33086512 | Intervention or Exposure
944 | Raab R, Hoffmann J, Spies M, Are pre- and early pregnancy lifestyle factors associated with the risk of preterm birth? A secondary cohort analysis of the cluster-randomised GeliS trial. BMC Pregnancy Childbirth. Mar 21 2022;22(1):230. doi: 10.1186/s12884-022-04513-5 35313852 | Outcome; Comparator
945 | Rabbani B, Chiti H, Sharifi F, Mazloomzadeh S. Effect of lifestyle modification for two years on obesity and metabolic syndrome components in elementary students: A community- based trial. Caspian J Intern Med. Summer 2022;13(3):555–566. doi:10.22088/cjim.13.3.555 | Intervention or Exposure; Country
946 | Racette SB, Barry VG, Bales CW, Nutritional quality of calorie restricted diets in the CALERIE 1 trial. Exp Gerontol. Aug 2022;165:111840. doi:10.1016/j.exger.2022.111840 35643360 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
947 | Raducha D, Ratajczak J, Jackowski T, Effects of 12-Month Interdisciplinary Interventions in 8- and 9-Year-Old Children with Excess Body Weight. Article. Int J Environ Res Public Health. Nov 29 2022;19(23)doi:10.3390/ijerph192315899 | Study design; Intervention or Exposure
948 | Radulescu A, Killian M, Kang Q, Yuan Q, Softie S. Dietary Counseling Aimed at Reducing Sugar Intake Yields the Greatest Improvement in Management of Weight and Metabolic Dysfunction in Children with Obesity. Article. Nutrients. Apr 3 2022;14(7)doi:10.3390/nu14071500 | Intervention or Exposure; Comparator
949 | Rai SK, Gortmaker SL, Hu FB, A South Asian Mediterranean-style diet is associated with favorable adiposity measures and lower diabetes risk: The MASALA cohort. Obesity. Jun 2023;31(6):1697–1706. doi: 10.1002/oby.23759 37203330 | Size or Power
950 | Rajabzadeh-Dehkordi M, Mohammadi-Nasrabadi F, Nouri M, Ahmadi A, Faghih S. Food insecurity, body mass index, socio-economic status, and food intake in lactating and non-lactating mothers with children under two years. BMC Nutr. Apr 17 2023;9(1):62. doi:10.1186/s40795-023-00718-9 37069651 | Study design; Outcome
951 | Rakhra V, Galappaththy SL, Bulchandani S, Cabandugama PK. Obesity and the Western Diet: How We Got Here. Article. Missouri medicine. 2020;117(6):536–538.33311784 | Study design; Publication status
952 | Ramezan M, Asghari G, Mirmiran P, Tahmasebinejad Z, Azizi F. Mediterranean dietary patterns and risk of type 2 diabetes in the Islamic Republic of Iran. East Mediterr Health J. Dec 29 2019;25(12):896–904. doi:10.26719/emhj.19.035 32003448 | Outcome
953 | Ramirez-Manent Jl, Tomas-Gil P, Marti-Lliteras P, Coll Villalonga JL, Martinez-Almoyna Rifa E, Lopez-Gonzalez AA. Dietary Intervention on Overweight and Obesity after Confinement by COVID-19. Nutrients. Feb 11 2023;15(4)doi:10.3390/nu15040912 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
954 | Ramos-Lopez O, Cuervo M, Goni L, Milagro FI, Riezu-Boj Jl, Martinez JA. Modeling of an integrative prototype based on genetic, phenotypic, and environmental information for personalized prescription of energy-restricted diets in overweight/obese subjects. Journal: Article. Am J Clin Nutr. Feb 1 2020;111(2):459–470. doi:10.1093/ajcn/nqz286 31751449 | Intervention or Exposure - Foods/Beverages Not Reported
955 | Ramos-Lopez O, Riezu-Boj Jl, Milagro FI, Cuervo M, Goni L, Martinez JA. Models Integrating Genetic and Lifestyle Interactions on Two Adiposity Phenotypes for Personalized Prescription of Energy-Restricted Diets With Different Macronutrient Distribution. Journal: Article. Front Genet. 2019;10(JUL):686. doi:10.3389/fgene.2019.00686 31417605 | Intervention or Exposure - Foods/Beverages Not Reported
956 | Rassy N, Van Straaten A, Carette C, Hamer M, Rives-Lange C, Czernichow S. Association of Healthy Lifestyle Factors and Obesity-Related Diseases in Adults in the UK. JAMA Netw Open. May 1 2023;6(5):e2314741. doi:10.1001/jamanetworkopen.2023.14741 37234008 | Intervention or Exposure; Outcome
957 | Ratshikombo T, Goedecke JH, Soboyisi M, Sex Differences in the Associations of Nutrient Patterns with Total and Regional Adiposity: A Study of Middle-Aged Black South African Men and Women. Article. Nutrients. Dec 20 2021;13(12)doi:10.3390/nu13124558 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
958 | Ratteree K, Yang S, Courville AB, Adults with alcohol use disorder may overreport dietary intake using the 1-year Diet History Questionnaire II. Article. Nutr Res. Jul 2019;67:53–59. doi:10.1016/j.nutres.2019.05.002 31158738 | Study design; Intervention or Exposure; Outcome
959 | Raynor HA, Mazzeo SE, LaRose JG, Effect of a High-Intensity Dietary Intervention on Changes in Dietary Intake and Eating Pathology during a Multicomponent Adolescent Obesity Intervention. Article. Nutrients. May 28 2021;13(6)doi:10.3390/nu13061850 | Study design; Intervention or Exposure; Outcome
960 | Razack M, Parambath VA, Rajanbabu B. The relationship between weight gain in exclusively breastfed babies and maternal diet. J Family Med Prim Care. Dec 2019;8(12):3832–3839. doi:10.4103/jfmpc.jfmpc_613_19 31879621 | Outcome; Comparator
961 | Rea K, Jadallah J, Nadpara P, Goode JK. Evaluation of the impact of a community-based, pharmacist-led weight loss program focused on a high-protein diet on risk factors for cardiovascular disease. Article. J Am Pharm Assoc (2003). Jul-Aug 2021;61(4S):S147–S153. doi: 10.1016/j.japh.2021.01.027 33618987 | Study design; Intervention or Exposure
962 | Rebholz CM, Kim H, Ma J, Jacques PF, Levy D, Lichtenstein AH. Diet Indices Reflecting Changes to Dietary Guidelines for Americans from 1990 to 2015 Are More Strongly Associated with Risk of Coronary Artery Disease Than the 1990 Diet Index. Curr Dev Nutr. Dec 2019;3(12):nzz123. doi:10.1093/cdn/nzz123 32154494 | Outcome
963 | Reddy NK, Kaushal V, Kanaya AM, Kandula NR, Gujral UP, Shah NS. Cardiovascular risk factor profiles in North and South Indian and Pakistani Americans: The MASALA Study. Am Heart J. Feb 2022;244:14–18. doi: 10.1016/j.ahj.2021.10.115 34688649 | Intervention or Exposure; Comparator
964 | Reginato E, Pippi R, Aiello C, Effect of Short Term Intensive Lifestyle Intervention on Hepatic Steatosis Indexes in Adults with Obesity and/or Type 2 Diabetes. Article. J Clin Med. Jun 14 2019;8(6)doi:10.3390/jcm8060851 | Intervention or Exposure; Health Status
965 | Reyes-Lopez MA, Gonzalez-Leyva CP, Rodriguez-Cano AM, Diet Quality Is Associated with a High Newborn Size and Reduction in the Risk of Low Birth Weight and Small for Gestational Age in a Group of Mexican Pregnant Women: An Observational Study. Article. Nutrients. May 28 2021;13(6)doi:10.3390/nu13061853 | Did not account for at least 1 key confounder
966 | Rhee DK, Ji Y, Hong X, Pearson C, Wang X, Caulfield LE. Mediterranean-Style Diet and Birth Outcomes in an Urban, Multiethnic, and Low-Income US Population. Nutrients. Apr 3 2021;13(4)doi:10.3390/nu13041188 | Outcome
967 | Ribas SA, Paravidino VB, Brandao JM, Santana da Silva LC. The Cardiovascular Health Integrated Lifestyle Diet (CHILD) Lowers LDL-Cholesterol Levels in Brazilian Dyslipidemic Pediatric Patients. J Am Nutr Assoc. May-Jun 2022;41(4):352–359. doi: 10.1080/07315724.2021.1887006 33683168 | Intervention or Exposure - Foods/Beverages Not Reported
968 | Ribo-Coll M, Casas R, Roth I, Estruch R. The relationship between consumption of fermented alcoholic beverages, eating patterns ans anthropometric parameters in elderly patients at high cardiovascular risk. Journal: Conference Abstract. Proceedings of the Nutrition Society. 2020;79(OCE2) | Intervention or Exposure; Publication status
969 | Ribo-Coll M, Lassale C, Sacanella E, Mediterranean diet and antihypertensive drug use: a randomized controlled trial. J Hypertens. Jun 1 2021;39(6):1230–1237. doi:10.1097/HJH.0000000000002765 33496530 | Outcome; Comparator
970 | Richardson LA, Basu A, Chien LC, Alman AC, Snell-Bergeon JK. Longitudinal Associations of Healthy Dietary Pattern Scores with Coronary Artery Calcification and Pericardial Adiposity in United States Adults with and without Type 1 Diabetes. J Nutr. Jul 2023;153(7):2085–2093. doi: 10.1016/j.tjnut.2023.05.016 37187353 | Outcome
971 | Rinott E, Meir AY, Tsaban G, The effects of the Green-Mediterranean diet on cardiometabolic health are linked to gut microbiome modifications: a randomized controlled trial. Genome Med. Mar 10 2022;14(1):29. doi: 10.1186/s13073-022-01015-z 35264213 | Comparator
972 | Riseberg E, Lopez-Cepero A, Mangano KM, Tucker KL, Mattei J. Specific Dietary Protein Sources Are Associated with Cardiometabolic Risk Factors in the Boston Puerto Rican Health Study. Article. J Acad Nutr Diet. Feb 2022;122(2):298–308 e3. doi:10.1016/j.jand.2021.05.020 34144919 | Intervention or Exposure
973 | Robson SM, Ziegler ML, McCullough MB, Changes in diet quality and home food environment in preschool children following weight management. Journal: Article. Int J Behav Nutr Phys Act. Feb 4 2019;16(1):16. doi: 10.1186/s12966-019-0777-6 30717746 | Outcome
974 | Rock CL, Zunshine E, Nguyen HT, Effects of Pistachio Consumption in a Behavioral Weight Loss Intervention on Weight Change, Cardiometabolic Factors, and Dietary Intake. Nutrients. Jul 20 2020;12(7)doi:10.3390/nu12072155 | Intervention or Exposure
975 | Rodrigues D, Carmo A, Gama A, The Great Recession weighted on Portuguese children: A structural equation modeling approach considering eating patterns. Am J Hum Biol. May 2022;34(5):e23692. doi: 10.1002/ajhb.23692 34669227 | Study design
976 | Rodrigues LC, Mota JF, Corgosinho FC, Nutrient intake is a predictor of lung function in obese asthmatic adolescents undergoing interdisciplinary therapy. British Journal of Nutrition. 2019;122(9):974–985.31317842 | Intervention or Exposure - Foods/Beverages Not Reported
977 | Rodriguez-Cano AM, Gonzalez-Ludlow I, Suarez-Rico BV, Ultra-Processed Food Consumption during Pregnancy and Its Association with Maternal Oxidative Stress Markers. Antioxidants (Basel). Jul 21 2022;11(7)doi:10.3390/antiox11071415 | Intervention or Exposure - Foods/Beverages Not Reported
978 | Rodriguez-Rodriguez E, Lopez-Sobaler AM, Ortega RM, Delgado-Losada ML, Lopez-Parra AM, Aparicio A. Association between Neutrophil-to-Lymphocyte Ratio with Abdominal Obesity and Healthy Eating Index in a Representative Older Spanish Population. Nutrients. Mar 23 2020;12(3)doi:10.3390/nu12030855 | Study design
979 | Rohatgi KW, Tinius RA, Cade WT, Steele EM, Cahill AG, Parra DC. Relationships between consumption of ultra-processed foods, gestational weight gain and neonatal outcomes in a sample of US pregnant women. PeerJ. 2017;5(2167–8359 (Print)):e4091. doi:10.7717/peerj.4091 29230355 | Outcome
980 | Rohling M, Martin K, Ellinger S, Schreiber M, Martin S, Kempf K. Weight reduction by the low-insulin-method— a randomized controlled trial. Article. Nutrients. 2020;12(10):1–17. | Intervention or Exposure
981 | Rolf K, Santoro A, Martucci M, Pietruszka B. The Association of Nutrition Quality with Frailty Syndrome among the Elderly. Article. Int J Environ Res Public Health. Mar 13 2022; 19(6)doi: 10.3390/ijerph19063379 | Study design; Intervention or Exposure; Outcome
982 | Rollo ME, Baldwin JN, Hutchesson M, The Feasibility and Preliminary Efficacy of an eHealth Lifestyle Program in Women with Recent Gestational Diabetes Mellitus: A Pilot Study. Int J Environ Res Public Health. Sep 28 2020;17(19)doi: 10.3390/ijerph17197115 | Intervention or Exposure; Health Status- 100% Diabetes; Comparator
983 | Romanidou M, Tripsianis G, Hershey MS, Association of the Modified Mediterranean Diet Score (mMDS) with Anthropometric and Biochemical Indices in US Career Firefighters. Nutrients. Nov 30 2020;12(12)doi:10.3390/nu12123693 | Study design
984 | Ronca A, Pellegrini N, Pagliai G, Effects of a dietary intervention with Mediterranean vs lacto-ovo vegetarian diets on HDL function: Results from the CARDIVEG study. Article. Nutr Metab Cardiovasc Dis. Mar 2023;33(3):651–658. doi:10.1016/j.numecd.2022.11.012 36642608 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
985 | Rosal MC, Lemon SC, Borg A, The Healthy Kids & Families study: Outcomes of a 24-month childhood obesity prevention intervention. Article. Prev Med Rep. Feb 2023;31:102086. doi:10.1016/j.pmedr.2022.102086 36820371 | Intervention or Exposure
986 | Rosas LG, Lv N, Xiao L, Effect of a Culturally Adapted Behavioral Intervention for Latino Adults on Weight Loss Over 2 Years: A Randomized Clinical Trial. JAMA Netw Open. Dec 1 2020;3(12):e2027744. doi:10.1001/jamanetworkopen.2020.27744 33337491 | Intervention or Exposure
987 | Rosi A, Calestani MV, Parrino L, Weight Status Is Related with Gender and Sleep Duration but Not with Dietary Habits and Physical Activity in Primary School Italian Children. Article. Nutrients. Jun 6 2017;9(6)doi:10.3390/nu9060579 | Study design
988 | Rosi A, Tesan M, Cremonini A, Body weight of individuals with obesity decreases after a 6-month high pasta or low pasta Mediterranean diet weight-loss intervention. Nutr Metab Cardiovasc Dis. Jun 9 2020;30(6):984–995. doi:10.1016/j.numecd.2020.02.013 32402585 | Intervention or Exposure; Comparator
989 | Rostgaard-Hansen AL, Lau CJ, Halkjaer J, Olsen A, Toft U. An updated validation of the Dietary Quality Score: associations with risk factors for cardiometabolic diseases in a Danish population. Eur J Nutr. Jun 2023;62(4): 1647–1656. doi:10.1007/s00394-023-03100-4 36739568 | Study design; Outcome
990 | Rotman SA, Fowler LA, Ray MK, Family Encouragement of Healthy Eating Predicts Child Dietary Intake and Weight Loss in Family-Based Behavioral Weight-Loss Treatment. Child Obes. Apr 2020;16(3):218–225. doi:10.1089/chi.2019.0119 31829732 | Intervention or Exposure; Outcome; Comparator
991 | Rotolo O, Zinzi I, Veronese N, Women in LOVe: Lacto-Ovo-Vegetarian Diet Rich in Omega-3 Improves Vasomotor Symptoms in Postmenopausal Women. An Exploratory Randomized Controlled Trial. Journal Article; Randomized Controlled Trial. Endocr Metab Immune Disord Drug Targets. 2019;19(8):1232–1239. doi:10.2174/1871530319666190528101532 31132980 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
992 | Roumi Z, Djazayery A, Keshavarz SA. Association Between Infants Anthropometric Outcomes With Maternal AHEI-P and Dll Scores. Clin Nutr Res. Apr 2023;12(2):116–125. doi:10.7762/cnr.2023.12.2.116 37214783 | Outcome
993 | Ruebel ML, Gilley SP, Sims CR, Associations between Maternal Diet, Body Composition and Gut Microbial Ecology in Pregnancy. Article. Nutrients. Sep 21 2021;13(9)doi:10.3390/nu13093295 | Intervention or Exposure; Comparator
994 | Rueda-Galindo L, Zeron-Rugerio MF, Egea AJS, Serrancoli G, Izquierdo-Pulido M. A Mediterranean-Style Diet Plan Is Associated with Greater Effectiveness and Sustainability in Weight Loss in Patients with Obesity after Endoscopic Bariatric Therapy. MedicinaLithuania. Feb 2022;58(2)doi:ARTN 168 | Health Status- 100% Hospitalized/Surgical
995 | Ruggieri S, Drago G, Panunzi S, The Influence of Sociodemographic Factors, Lifestyle, and Risk Perception on Dietary Patterns in Pregnant Women Living in Highly Contaminated Areas: Data from the NEHO Birth Cohort. Nutrients. Aug 25 2022;14(17)doi: 10.3390/nu14173489 | Outcome
996 | Ruggiero E, Mignogna C, Costanzo S, Changes in the consumption of foods characterising the Mediterranean dietary pattern and major correlates during the COVID-19 confinement in Italy: results from two cohort studies. Int J Food Sci Nutr. Dec 2021;72(8):1105–1117. doi:10.1080/09637486.2021.1895726 33823720 | Outcome
997 | Rumbo-Rodriguez L, Zaragoza-Marti A, Sanchez-SanSegundo M, Ferrer-Cascales R, Laguna-Perez A, Hurtado-Sanchez JA. Effectiveness of a Two-Year Multicomponent Intervention for the Treatment of Overweight and Obesity in Older People. Nutrients. Nov 11 2022;14(22)doi: 10.3390/nu14224762 | Intervention or Exposure; Outcome
998 | Rybak TM, Goetz AR, Stark LJ. Examining patterns of postnatal feeding in relation to infant's weight during the first year. Article. Appetite. Nov 1 2021;166:105473. doi:10.1016/j.appet.2021.105473 34153422 | Intervention or Exposure
999 | Sadeghi A, Tabatabaiee M, Mousavi MA, Mousavi SN, Abdollahi Sabet S, Jalili N. Dietary Pattern or Weight Loss: Which One Is More Important to Reduce Disease Activity Score in Patients with Rheumatoid Arthritis? A Randomized Feeding Trial. Int J Clin Pract. 2022;2022:6004916. doi:10.1155/2022/6004916 35685522 | Intervention or Exposure - Foods/Beverages Not Reported; Health Status
1000 | Sadeghi A, Zarrinjooiee G, Mousavi SN, Abdollahi Sabet S, Jalili N. Effects of a Mediterranean Diet Compared with the Low-Fat Diet on Patients with Knee Osteoarthritis: A Randomized Feeding Trial. Int J Clin Pract. 2022;2022:7275192. doi: 10.1155/2022/7275192 35685492 | Intervention or Exposure - Foods/Beverages Not Reported
1001 | Said MS, El Sayed IT, Ibrahim EE, Khafagy GM. Effect of DASH Diet Versus Healthy Dietary Advice on the Estimated Atherosclerotic Cardiovascular Disease Risk. J Prim Care Community Health. Jan-Dec 2021;12:2150132720980952. doi: 10.1177/2150132720980952 33632022 | Intervention or Exposure - Foods/Beverages Not Reported
1002 | Saidj S, Ruchat SM, Henderson M, Drapeau V, Mathieu ME. Which healthy lifestyle habits mitigate the risk of obesity and cardiometabolic risk factors in Caucasian children exposed to in utero adverse gestational factors? Nutr Metab Cardiovasc Dis. Jan 4 2021;31(1):286–296. doi:10.1016/j.numecd.2020.08.008 33121841 | Study design; Intervention or Exposure
1003 | Sakurai M, Ishizaki M, Morikawa Y, Frequency of consumption of balanced meals, bodyweight gain and incident risk of glucose intolerance in Japanese men and women: A cohort study. J Diabetes Investig. May 2021;12(5):763–770. doi: 10.1111/jdi.13392 | Intervention or Exposure
1004 | Sal S, Bektas M. Effectiveness of Obesity Prevention Program Developed for Secondary School Students. American Journal of Health Education. 2022;53(1):45–55. | Study design; Intervention or Exposure
1005 | Salamanca-Gonzalez P, Valls-Zamora RM, Pedret-Figuerola A, Effectiveness of a Motivational Nutritional Intervention through Social Networks 2.0 to Increase Adherence to the Mediterranean Diet and Improve Lung Function in Active Smokers: The DIET Study, a Randomized, Controlled and Parallel Clinical Trial in Primary Care. Article. Nutrients. Oct 14 2021;13(10)doi:10.3390/nu13103597 | Intervention or Exposure; Outcome
1006 | Salas-Salvado J, Diaz-Lopez A, Ruiz-Canela M, Effect of a Lifestyle Intervention Program With Energy-Restricted Mediterranean Diet and Exercise on Weight Loss and Cardiovascular Risk Factors: One-Year Results of the PREDIMED-Plus Trial. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Diabetes Care. May 2019;42(5):777–788. doi: 10.2337/dc18-0836 30389673 | Intervention or Exposure; Comparator
1007 | Salavati N, Vinke PC, Lewis F, Bakker MK, Erwich J, E MvdB. Offspring Birth Weight Is Associated with Specific Preconception Maternal Food Group Intake: Data from a Linked Population-Based Birth Cohort. Nutrients. Oct 16 2020;12(10)doi:10.3390/nu12103172 | Intervention or Exposure; Outcome
1008 | Saldiva S, De Arruda Neta A, Teixeira JA, Dietary Pattern Influences Gestational Weight Gain: Results from the ProcriAr Cohort Study-Sao Paulo, Brazil. Nutrients. Oct 21 2022;14(20)doi:10.3390/nu14204428 | Outcome
1009 | Sallinen T, Viitasalo A, Lintu N, The effects of an 8-year individualised lifestyle intervention on food consumption and nutrient intake from childhood to adolescence: the PANIC Study. Article. J Nutr Sci. 2022;11:e40. doi:10.1017/jns.2022.13 35720174 | Intervention or Exposure; Outcome
1010 | Salomon C, Bellamy J, Evans E, 'Get Healthy!' physical activity and healthy eating intervention for adults with intellectual disability: results from the feasibility pilot. Pilot Feasibility Stud. Mar 22 2023;9(1):48. doi: 10.1186/s40814-023-01267-5 36949532 | Study design; Intervention or Exposure
1011 | Samano R, Martinez-Rojano H, Ortiz-Hernandez L, Dietary and Nutrient Intake, Eating Habits, and Its Association with Maternal Gestational Weight Gain and Offspring's Birth Weight in Pregnant Adolescents. Nutrients. Oct 28 2022;14(21)doi: 10.3390/nu14214545 | Intervention or Exposure
1012 | San Mauro Martin I, Sanz Rojo S, Becerra X, Garicano Vilar E. Successful Implementation of a Mediterranean Weight Loss Program to Prevent Overweight and Obesity in the Workplace. Journal Article; Pragmatic Clinical Trial; Research Support, Non-U.S. Gov't. J Occup Environ Med. Aug 2019;61(8):e329–e332. doi:10.1097/JOM.0000000000001628 31090674 | Study design
1013 | Sanchez-Flack JC, Tussing-Humphreys L, Lamar M, Building research in diet and cognition (BRIDGE): Baseline characteristics of older obese African American adults in a randomized controlled trial to examine the effect of the Mediterranean diet with and without weight loss on cognitive functioning. Prev Med Rep. Jun 2021;22:101302. doi:10.1016/j.pmedr.2020.101302 33665063 | Study design; Outcome
1014 | Sanchez-Martinez F, Brugueras S, Serral G, Three-Year Follow-Up of the POIBA Intervention on Childhood Obesity: A QuasiExperimental Study. Nutrients. Jan 29 2021;13(2)doi:10.3390/nu13020453 | Intervention or Exposure
1015 | Sandoval-lnsausti H, Jimenez-Onsurbe M, Donat-Vargas C, Ultra-Processed Food Consumption Is Associated with Abdominal Obesity: A Prospective Cohort Study in Older Adults. Nutrients. Aug 7 2020;12(8)doi:10.3390/nu12082368 | Size or Power
1016 | Sandvik P, Ek A, Eli K, Somaraki M, Bottai M, Nowicka P. Picky eating in an obesity intervention for preschool-aged children - What role does it play, and does the measurement instrument matter? Article. International Journal of Behavioral Nutrition and Physical Activity. 2019;16(1) | Intervention or Exposure
1017 | Sandvik P, Kuronen S, Richards HR, Associations of preschoolers' dietary patterns with eating behaviors and parental feeding practices at a 12-month follow-up of obesity treatment. Appetite. Jan 1 2022;168 doi:ARTN 105724 | Study design
1018 | Sanllorente A, Soria-Florido MT, Castaner O, A lifestyle intervention with an energy-restricted Mediterranean diet and physical activity enhances HDL function: a substudy of the PREDIMED-Plus randomized controlled trial. Am J Clin Nutr. Nov 8 2021;114(5):1666–1674. doi: 10.1093/ajcn/nqab246 34582548 | Intervention or Exposure; Outcome
1019 | Santana JDM, Queiroz VO, Pereira M Associations between maternal dietary patterns and infant birth weight in the nisami cohort: A structural equation modeling analysis. Nutrients. 2021. 13:.10.3390/nu13114054 | Outcome
1020 | Santiago-Torres M, Shi Z, Tinker LF, Diet quality indices and risk of metabolic syndrome among postmenopausal women of Mexican ethnic descent in the Women's Health Initiative Observational Study. Nutr Healthy Aging. Nov 3 2020;5(4):261–272. doi: 10.3233/NHA-190076 33367152 | Size or Power
1021 | Santi-Cano MJ, Novalbos-Ruiz JP, Bernal-Jimenez MA, Bibiloni MDM, Tur JA, Rodriguez Martin A. Association of Adherence to Specific Mediterranean Diet Components and Cardiorespiratory Fitness in Young Adults. Nutrients. Mar 15 2020;12(3)doi:10.3390/nu12030776 | Study design
1022 | Santos A, Rodrigues A, Rosa LPS, Noll M, Silveira EA. Traditional Brazilian Diet and Olive Oil Reduce Cardiometabolic Risk Factors in Severely Obese Individuals: A Randomized Trial. Nutrients. May 14 2020;12(5)doi:10.3390/nu12051413 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
1023 | Santos IDS, Crivellenti LC, Franco LJ, Sartorelli DS. Relationship between the quality of the pregnant woman's diet and birth weight: a prospective cohort study. Eur J Clin Nutr. Dec 2021;75(12):1819–1828. doi:10.1038/s41430-021-00894-6 33742155 | Study design
1024 | Santulli G, Pascale V, Finelli R, We are what we eat: Impact of food from short supply chain on metabolic syndrome. Article. Journal of Clinical Medicine. 2019;8(12) | Study design
1025 | Sarac J, Havas Augustin D, Lovric M, A Generation Shift in Mediterranean Diet Adherence and Its Association with Biological Markers and Health in Dalmatia, Croatia. Article. Nutrients. Dec 20 2021;13(12)doi:10.3390/nu13124564 | Study design
1026 | Sarebanhassanabadi M, Shahriari Kalantari M, Boffetta P, Dietary habits and the 10-year risk of overweight and obesity in urban adult population: A cohort study predicated on Yazd Healthy Heart Project. Article. Diabetes Metab Syndr. Sep-Oct 2020;14(5):1391–1397. doi:10.1016/j.dsx.2020.07.024 32755840 | Country
1027 | Saslow LR, Jones LM, Sen A, Comparing Very Low-Carbohydrate vs DASH Diets for Overweight or Obese Adults With Hypertension and Prediabetes or Type 2 Diabetes: A Randomized Trial. Ann Fam Med. May-Jun 2023;21(3):256–263. doi: 10.1370/afm.2968 37217318 | Intervention or Exposure - Foods/Beverages Not Reported
1028 | Sauder KA, Bekelman TA, Harrall KK, Glueck DH, Dabelea D. Gestational diabetes exposure and adiposity outcomes in childhood and adolescence: An analysis of effect modification by breastfeeding, diet quality, and physical activity in the EPOCH study. Pediatr Obes. Dec 2019;14(12):e12562. doi: 10.1111/ijpo.12562 31274243 | Intervention or Exposure; Outcome
1029 | Savard C, Lemieux S, Carbonneau E, Trimester-Specific Assessment of Diet Quality in a Sample of Canadian Pregnant Women. Article. Int J Environ Res Public Health. Jan 24 2019;16(3)doi: 10.3390/ijerph16030311 | Outcome
1030 | Sawicki CM, Lichtenstein AH, Rogers GT, Comparison of Indices of Carbohydrate Quality and Food Sources of Dietary Fiber on Longitudinal Changes in Waist Circumference in the Framingham Offspring Cohort. Nutrients. Mar 19 2021;13(3):997. doi: 10.3390/nu13030997 33808767 | Intervention or Exposure
1031 | Schlaff RA, Baruth M, Deere SJ, Boggs A, Odabasic A. Associations between prenatal diet quality and gestational weight gain. Nutr Health. Mar 2020;26(1):13–18. doi:10.1177/0260106020903926 32056480 | Outcome
1032 | Schmidt KA, Jones RB, Rios C, Clinical Intervention to Reduce Dietary Sugar Does Not Affect Liver Fat in Latino Youth, Regardless of | Intervention or Exposure
1033 | Schnermann ME, Schulz CA, Herder C, Alexy U, Nothlings U. A lifestyle pattern during adolescence is associated with cardiovascular risk markers in young adults: results from the DONALD cohort study. J Nutr Sci. 2021;10:e92. doi: 10.1017/jns.2021.84 34733504 | Intervention or Exposure
1034 | Schnermann ME, Schulz CA, Perrar I, A healthy lifestyle during adolescence was inversely associated with fatty liver indices in early adulthood: findings from the DONALD cohort study. Br J Nutr. Feb 14 2023;129(3):513–522. doi:10.1017/S0007114522001313 35492013 | Intervention or Exposure; Outcome
1035 | Schuler BR, Fowler B, Rubio D, Building Blocks for Healthy Children: Evaluation of a Child Care Center-Based Obesity Prevention Pilot Among Low-Income Children. Article. Journal of nutrition education and behavior. 2019;51(8):958–966.31229396 | Intervention or Exposure; Outcome
1036 | Schulpen M, van den Brandt PA. Adherence to the Mediterranean Diet and Risks of Prostate and Bladder Cancer in the Netherlands Cohort Study. Article. Cancer Epidemiol Biomarkers Prev. Sep 2019;28(9):1480–1488. doi:10.1158/1055-9965.EPI-19-0224 31235470 | Outcome
1037 | Schutte S, Esser D, Siebelink E, Diverging metabolic effects of 2 energy-restricted diets differing in nutrient quality: a 12-week randomized controlled trial in subjects with abdominal obesity. Am J Clin Nutr. Jul 6 2022;116(1):132–150. doi:10.1093/ajcn/nqac025 35102369 | Size or Power
1038 | Scott E, Shehata M, Panesar A, Summers C, Dale J. The Low Carb Program for people with type 2 diabetes and pre-diabetes: a mixed methods feasibility study of signposting from general practice. Article. BJGP Open. Mar 2022;6(1):1–10. doi:10.3399/BJGP0.2021.0137 | Study design; Intervention or Exposure; Health Status- 100% Diabetes
1039 | Seconda L, Egnell M, Julia C, Association between sustainable dietary patterns and body weight, overweight, and obesity risk in the NutriNet-Sante prospective cohort. Am J Clin Nutr. Jul 1 2020;112(1):138–149. doi:10.1093/ajcn/nqz259 31725157 | Intervention or Exposure - Foods/Beverages Not Reported
1040 | Sedin A, Landin Olsson M, Cloetens L. The effects of 2-year consumption of a new Nordic diet on weight loss maintenance in subjects with obesity: a randomised controlled intervention study. Journal: Conference Abstract. Obesity reviews. 2020;21(SUPPL 1) | Publication status
1041 | Seguin-Fowler RA, Eldridge GD, Rethorst CD, Improvements and Maintenance of Clinical and Functional Measures Among Rural Women: Strong Hearts, Healthy Communities-2. 0 Cluster Randomized Trial. Article. Circ Cardiovasc Oual Outcomes. Nov 2022;15(11):e009333. doi:10.1161/CIRCOUTCOMES.122.009333 | Intervention or Exposure
1042 | Seral-Cortes M, Sabroso-Lasa S, Bailo-Aysa A, Mediterranean Diet, Screen-Time-Based Sedentary Behavior and Their Interaction Effect on Adiposity in European Adolescents: The HELENA Study. Nutrients. Jan 30 2021;13(2)doi:10.3390/nu13020474 | Study design
1043 | Seral-Cortes M, Sabroso-Lasa S, De Miguel-Etayo P, Interaction Effect of the Mediterranean Diet and an Obesity Genetic Risk Score on Adiposity and Metabolic Syndrome in Adolescents: The HELENA Study. Nutrients. Dec 16 2020;12(12)doi:10.3390/nu12123841 | Study design
1044 | Seremet Kurklu N, Karatas Torun N, Ozen Kucukcetin I, Akyol A. Is there a relationship between the dietary inflammatory index and metabolic syndrome among adolescents? Article. Journal of Pediatric Endocrinology and Metabolism. 2020;33(4):495–502.32084004 | Intervention or Exposure - Foods/Beverages Not Reported
1045 | Serra MC, Beavers DP, Henderson RM, Kelleher JL, Kiel JR, Beavers KM. Effects of a Hypocaloric, Nutritionally Complete, Higher Protein Meal Plan on Regional Body Fat and Cardiometabolic Biomarkers in Older Adults with Obesity. Article. Ann Nutr Metab. 2019;74(2):149–155. doi:10.1159/000497066 30754039 | Intervention or Exposure - Foods/Beverages Not Reported
1046 | Setiawan EA, Rianda D, Kadim M, Tenth year reenrollment randomized trial investigating the effects of childhood probiotics and calcium supplementation on height and weight at adolescence. Sci Rep. Jun 4 2021;11(1):11860. doi: 10.1038/s41598-021-88819-y 34088920 | Intervention or Exposure
1047 | Setiono FJ, Jock B, Trude A, Associations between Food Consumption Patterns and Chronic Diseases and Self-Reported Morbidities in 6 American Indian Communities. Article. Current Developments in Nutrition. 2019;3:69–80. | Study design
1048 | Seyam MK, Alqahtani M, Sirajudeen MS, Muthusamy H, Kashoo FZ, Salah MM. Effect of circuit training with low-carbohydrate diet on body composition, cardiometabolic indices, and exercise capacity in adults with mild to moderate obesity in Saudi Arabia: A randomized control trial. Article. Medicine (Baltimore). Aug 19 2022;101(33):e30054. doi:10.1097/MD.0000000000030054 35984171 | Intervention or Exposure - Foods/Beverages Not Reported
1049 | Sezaki A, Imai T, Miyamoto K, Kawase F, Shimokata H. Mediterranean diet score and incidence of IHD: a global comparative study. Article. Public Health Nutr. Jun 2019;22(8):1444–1450. doi:10.1017/S1368980018003877 30744723 | Study design; Outcome
1050 | Shaalan A, Lee S, Feart C, Alterations in the Oral Microbiome Associated With Diabetes, Overweight, and Dietary Components. Front Nutr. 2022;9:914715. doi:10.3389/fnut.2022.914715 35873415 | Intervention or Exposure; Outcome
1051 | Shahinfar H, Djafari F, Babaei N, Cardiorespiratory fitness is positively associated with both healthy and western dietary pattern in Iranian middle-aged. Int J Vitam Nutr Res. Oct 2022;92(5–6):366–375. doi:10.1024/0300-9831/a000685 33143533 | Life stage
1052 | Shakeri M, Jafarirad S, Amani R, Cheraghian B, Najafian M. A longitudinal study on the relationship between mother's personality trait and eating behaviors, food intake, maternal weight gain during pregnancy and neonatal birth weight. Article. Nutrition Journal. 2020:19(1) | Intervention or Exposure
1053 | Shalabi H, Alotaibi A, Alqahtani A, Alattas H, Alghamdi Z. Ketogenic Diets: Side Effects, Attitude, and Quality of Life. Cureus. Dec 2021;13(12):e20390. doi:10.7759/cureus.20390 35036220 | Study design; Intervention or Exposure; Outcome
1054 | Shang X, Li Y, Xu H, Effect of multidimensional lifestyle interventions on metabolic risk reduction in children: a cluster randomised controlled trial. Journal: Article. Prev Med. Feb 3 2020;133:106010. doi:10.1016/j.ypmed.2020.106010 32027918 | Intervention or Exposure - Foods/Beverages Not Reported
1055 | Shang X, Li Y, Xu H, Leading dietary determinants identified using machine learning techniques and a healthy diet score for changes in cardiometabolic risk factors in children: a longitudinal analysis. Nutr J. Sep 19 2020;19(1):105. doi: 10.1186/s12937-020-00611-2 32950062 | Country
1056 | Shang X, Li Y, Xu H, Zhang Q, Liu A, Ma G. The Clustering of Low Diet Quality, Low Physical Fitness, and Unhealthy Sleep Pattern and Its Association with Changes in Cardiometabolic Risk Factors in Children. Nutrients. Feb 24 2020;12(2)doi:10.3390/nu12020591 | Country
1057 | Shapiro AL, Kaar JL, Crume TL, Maternal diet quality in pregnancy and neonatal adiposity: the Healthy Start Study. Int J Obes (Lond). Jul 2016;40(7):1056–62. doi: 10.1038/ijo.2016.79 27133623 | Did not account for at least 1 key confounder
1058 | Shaw Tronieri J, Wadden T, Sugimoto D, 25th European Congress on Obesity, Vienna, Austria, May 23–26, 2018: Abstracts. Journal article; Conference proceeding. Obes Facts. 2018;11 Suppl 1( Suppl 1): 1–364. doi: 10.1159/000489691 | Publication status
1059 | Shi H, Schweren LJS, Ter Horst R, Low-grade inflammation as mediator between diet and behavioral disinhibition: A UK Biobank study. Brain Behav Immun. Nov 2022;106:100–110. doi: 10.1016/j.bbi.2022.07.165 35944739 | Study design; Outcome
1060 | Shi J, Fang H, Cheng X, Nutrient Patterns and Its Association and Metabolic Syndrome among Chinese Children and Adolescents Aged 7–17. Article. Nutrients. Dec 27 2022;15(1)doi:10.3390/nu15010117 | Study design; Intervention or Exposure
1061 | Shi J, Fang H, Guo Q, Association of Dietary Patterns with Metabolic Syndrome in Chinese Children and Adolescents Aged 7–17: The China National Nutrition and Health Surveillance of Children and Lactating Mothers in 2016–2017. Nutrients. Aug 26 2022;14(17)doi:10.3390/nu14173524 | Study design
1062 | Shih CW, Hauser ME, Aronica L, Rigdon J, Gardner CD. Changes in blood lipid concentrations associated with changes in intake of dietary saturated fat in the context of a healthy low-carbohydrate weight-loss diet: a secondary analysis of the Diet Intervention Examining The Factors Interacting with Treatment Success (DIETFITS) trial. Journal Article; Randomized Controlled Trial; Research Support, N.I.H., Extramural. Am J Clin Nutr. Feb 1 2019;109(2):433–441. doi:10.1093/ajcn/nqy305 30649213 | Intervention or Exposure - Foods/Beverages Not Reported
1063 | Shiraishi M, Matsuzaki M, Tsunematsu R, Watanabe S, Kobayashi R, Haruna M. Effects of Individual Dietary Intervention on Nutrient Intake in Postpartum Japanese Women: A Randomized Controlled Trial. Article. Nutrients. Sep 19 2021;13(9)doi: 10.3390/nu13093272 | Intervention or Exposure; Outcome
1064 | Siega-Riz AM, Vladutiu CJ, Butera NM, Preconception Diet Quality Is Associated with Birth Weight for Gestational Age Among Women in the Hispanic Community Health Study/Study of Latinos. Article. J Acad Nutr Diet. Mar 2021;121(3):458–466. doi:10.1016/j.jand.2020.09.039 33187928 | Outcome
1065 | Silva CFM, Saunders C, Peres W, Effect of ultra-processed foods consumption on glycemic control and gestational weight gain in pregnant with pregestational diabetes mellitus using carbohydrate counting. Article. PeerJ. 2021;9:e10514. doi:10.7717/peerj.10514 33585080 | Intervention or Exposure - Foods/Beverages Not Reported; Health Status- 100% Diabetes
1066 | Silva CLD, Sousa AG, Borges L, Costa T. Usual consumption of ultra-processed foods and its association with sex, age, physical activity, and body mass index in adults living in Brasilia City, Brazil. Rev Bras Epidemiol. 2021;24:e210033. doi: 10.1590/1980-549720210033 34105596 | Study design
1067 | Silva D, Santos TSS, Conde WL, Slater B. Nutritional status and metabolic risk in adults: association with diet quality as assessed with ESQUADA. Rev Bras Epidemiol. 2021;24:e210019. Estado nutricional e risco metabolico em adultos: associacao com a qualidade da dieta medida pela ESQUADA. doi: 10.1590/1980-549720210019 | Study design
1068 | Silva Dos Santos F, Costa Mintem G, Oliveira de Oliveira I, Consumption of ultra-processed foods and interleukin-6 in two cohorts from high- and middle-income countries. Article. Br J Nutr. Feb 21 2022;129(9):1–11. doi:10.1017/S0007114522000551 | Size or Power
1069 | Silva Dos Santos F, Costa Mintem G, Oliveira de Oliveira I, Consumption of ultra-processed foods and IL-6 in two cohorts from high-and middle-income countries. BrJ Nutr. Feb 21 2022:1–11. doi:10.1017/S0007114522000551 | Intervention or Exposure; Outcome
1070 | Silva TR, Lago SC, Yavorivski A, Ferreira LL, Fighera TM, Spritzer PM. Effects of high protein, low-glycemic index diet on lean body mass, strength, and physical performance in late postmenopausal women: a randomized controlled trial. Menopause. Nov 16 2020;28(3):307–317. doi:10.1097/GME.0000000000001692 33201025 | Intervention or Exposure
1071 | Silver HJ, Olson D, Mayfield D, Effect of the glucagon-like peptide-1 receptor agonist liraglutide, compared to caloric restriction, on appetite, dietary intake, body fat distribution and cardiometabolic biomarkers: A randomized trial in adults with obesity and prediabetes. Diabetes Obes Metab. Aug 2023;25(8):2340–2350. doi:10.1111/dom.15113 37188932 | Intervention or Exposure
1072 | Silver RE, Roberts SB, Kramer AF, Chui KKH, Das SK. No Effect of Calorie Restriction or Dietary Patterns on Spatial Working Memory During a 2-Year Intervention: A Secondary Analysis of the CALERIE Trial. J Nutr. Mar 2023;153(3):733–740. doi: 10.1016/j.tjnut.2023.01.019 36805108 | Outcome
1073 | Simpson SA, Coulman E, Gallagher D, Healthy eating and lifestyle in pregnancy (HELP): a cluster randomised trial to evaluate the effectiveness of a weight management intervention for pregnant women with obesity on weight at 12 months postpartum. Int J Obes (Lond). Aug 2021;45(8):1728–1739. doi:10.1038/s41366-021-00835-0 34021264 | Intervention or Exposure
1074 | Singer J, Putulik Kidlapik C, Martin B, Dean HJ, Trepman E, Embil JM. Food consumption, obesity and abnormal glycaemic control in a Canadian Inuit community. Article. Clin Obes. Dec 2014;4(6):316–23. doi:10.1111/cob.12074 25826161 | Study design
1075 | Singh PN, Steinbach J, Nelson A, Incorporating an Increase in Plant-Based Food Choices into a Model of Culturally Responsive Care for Hispanic/Latino Children and Adults Who Are Overweight/Obese. Int J Environ Res Public Health. Jul 6 2020;17(13)doi:10.3390/ijerph17134849 | Study design
1076 | Sirkka O, Hof MH, Vrijkotte T, Feeding patterns and BMI trajectories during infancy: a multi-ethnic, prospective birth cohort. Article. BMC Pediatr. Jan 13 2021;21(1):34. doi: 10.1186/s12887-020-02456-4 33441111 | Intervention or Exposure
1077 | Sisay T, Tolessa T, Mekonen W. Changes in biochemical parameters by gender and time: Effect of short-term vegan diet adherence. PLoS One. 2020;15(8):e0237065. doi:10.1371/journal.pone.0237065 32785233 | Study design; Duration of Intervention; Country
1078 | Skelly LE, Barbour-Tuck EN, Kurgan N, Neutral Effect of Increased Dairy Product Intake, as Part of a Lifestyle Modification Program, on Cardiometabolic Health in Adolescent Girls With Overweight/Obesity: A Secondary Analysis From a Randomized Controlled Trial. Front Nutr. 2021;8:673589. doi:10.3389/fnut.2021.673589 34095194 | Intervention or Exposure; Outcome
1079 | Skjakodegard HF, Conlon RPK, Hystad SW, Family-based treatment of children with severe obesity in a public healthcare setting: Results from a randomized controlled trial. Article in Press. Clin Obes. Jun 2022;12(3):e12513. doi: 10.1111/cob.12513 35218145 | Intervention or Exposure
1080 | Skreden M, Hillesund ER, Wills AK, Brantsaeter AL, Bere E, Overby NC. Adherence to the New Nordic Diet during pregnancy and subsequent maternal weight development: a study conducted in the Norwegian Mother and Child Cohort Study (MoBa). Br J Nutr. Jun 2018;119(11):1286–1294. doi:10.1017/S0007114518000776 29770760 | Did not account for at least 1 key confounder
1081 | Slater K, Rollo ME, Szewczyk Z, Ashton L, Schumacher T, Collins C. Do the dietary intakes of pregnant women attending public hospital antenatal clinics align with australian guide to healthy eating recommendations? Article. Nutrients. 2020;12(8):1–14. | Outcome
1082 | Sliz D, Parol D, Wetnicki M, ChomiukT, Grabowska I. Macronutrient intake, carbohydrate metabolism and cholesterol in Polish male amateur athletes on a vegan diet. Nutrition Bulletin. 2021;46(2):120–127. | Study design
1083 | Slomski A. Low-Carb Diets Help Maintain Weight Loss. Article. JAMA. Jan 29 2019;321(4):335. doi: 10.1001/jama.2018.22031 | Publication status
1084 | Smit AJP, Hojeij B, Rousian M, A high periconceptional maternal ultra-processed food consumption impairs embryonic growth: The Rotterdam periconceptional cohort. Article. Clin Nutr. Aug 2022;41(8):1667–1675. doi:10.1016/j.clnu.2022.06.006 35772220 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
1085 | Smithers LG, Hedges J, Ribeiro Santiago PH, Jamieson LM. Dietary Intake and Anthropometric Measurement at Age 36 Months Among Aboriginal and/or Torres Strait Islander Children in Australia: A Secondary Analysis of the Baby Teeth Talk Randomized Clinical Trial. JAMA Netw Open. Jul 1 2021;4(7):e2114348. doi:10.1001/jamanetworkopen.2021.14348 34236413 | Intervention or Exposure
1086 | Sob C, Siegrist M, Hagmann D, Hartmann C. A longitudinal study examining the influence of diet-related compensatory behavior on healthy weight management. Appetite. Jan 1 2021;156:104975. doi:10.1016/j.appet.2020.104975 32966848 | Intervention or Exposure
1087 | Soepnel LM, Draper CE, Mabetha K, Evaluating implementation of the FIGO Nutrition Checklist for preconception and pregnancy within the Bukhali trial in Soweto, South Africa. Int J Gynaecol Obstet. Jan 2023;160 Suppl 1(Suppl 1):68–79. doi: 10.1002/ijgo.14541 36635078 | Intervention or Exposure; Outcome
1088 | Soldevila-Domenech N, Forcano L, Vintro-Alcaraz C, Interplay between cognition and weight reduction in individuals following a Mediterranean Diet: Three-year follow-up of the PREDIMED-Plus trial. Article. Clin Nutr. Sep 2021;40(9):5221–5237. doi: 10.1016/j.clnu.2021.07.020 34474192 | Intervention or Exposure; Comparator
1089 | Soldevila-Domenech N, Pastor A, Sala-Vila A, Sex differences in endocannabinoids during 3 years of Mediterranean diet intervention: Association with insulin resistance and weight loss in a population with metabolic syndrome. Front Nutr. 2022;9:1076677. doi:10.3389/fnut.2022.1076677 36532543 | Intervention or Exposure
1090 | Soliman GA, Kim J, Lee JM, Wellness programme at the workplace promotes dietary change and improves health indicators in a longitudinal retrospective study. Article. Public health nutrition. 2019;22(2):354–362.30269699 | Intervention or Exposure
1091 | Soltani S, Aminianfar A, Hajianfar H, Azadbakht L, Shahshahan Z, Esmaillzadeh A. Association between dietary inflammatory potential and risk of developing gestational diabetes: a prospective cohort study. Nutr J. Jun 2 2021;20(1):48. doi:10.1186/s12937-021-00705-5 34078385 | Intervention or Exposure
1092 | Sommersten CH, Gjerde ES, Laupsa-Borge J, Relationship between Ketones, Ghrelin, and, Appetite on Isocaloric Diets with Varying Carbohydrate Quality and Amount: Results from a Randomized Controlled Trial in People with Obesity (CARBFUNC). J Nutr. Feb 2023;153(2):459–469. doi: 10.1016/j.tjnut.2022.12.030 36894239 | Intervention or Exposure - Foods/Beverages Not Reported
1093 | Sommersten CH, Laupsa-Borge J, Andersen AIO, Diets differing in carbohydrate cellularity and amount similarly reduced visceral fat in people with obesity - a randomized controlled trial (CARBFUNC). Clin Nutr. Oct 2022;41(10):2345–2355. doi:10.1016/j.clnu.2022.08.028 36116147 | Intervention or Exposure
1094 | Soria-Contreras DC, Rifas-Shiman SL, Aris IM, Weight Trajectories After Delivery are Associated with Adiposity and Cardiometabolic Markers at 3 Years Postpartum Among Women in Project Viva. J Nutr. Jul 1 2020;150(7):1889–1898. doi: 10.1093/jn/nxaa104 32321175 | Life stage
1095 | Soto-Mota A, Pereira MA, Ebbeling CB, Aronica L, Ludwig DS. Evidence for the carbohydrate-insulin model in a reanalysis of the Diet Intervention Examining The Factors Interacting with Treatment Success (DIETFITS) trial. Am J Clin Nutr. Mar 2023;117(3):599–606. doi:10.1016/j.ajcnut.2022.12.014 36811468 | Intervention or Exposure - Foods/Beverages Not Reported
1096 | Sotos-Prieto M, Ortola R, Lopez-Garcia E, Rodriguez-Artalejo F, Garcia-Esquinas E. Adherence to the Mediterranean Diet and Physical Resilience in Older Adults: The Seniors-ENRICA Cohort. J Gerontol A Biol Sci Med Sci. Feb 25 2021;76(3):505–512. doi: 10.1093/gerona/glaa277 33152061 | Outcome
1097 | Sotos-Prieto M, Ortola R, Ruiz-Canela M, Association between the Mediterranean lifestyle, metabolic syndrome and mortality: a whole-country cohort in Spain. Cardiovascular Diabetology. Jan 5 2021;20(1)doi:ARTN 5 | Intervention or Exposure
1098 | Sotos-Prieto M, Struijk EA, Fung TT, Association between the quality of plant-based diets and risk of frailty. J Cachexia Sarcopenia Muscle. Dec 2022;13(6):2854–2862. doi:10.1002/jcsm.13077 36177985 | Outcome
1099 | Starling AP, Sauder KA, Kaar JL, Shapiro AL, Siega-Riz AM, Dabelea D. Maternal Dietary Patterns during Pregnancy Are Associated with Newborn Body Composition. Article. J Nutr. Jul 2017;147(7):1334–1339. doi:10.3945/jn.117.248948 28539412 | Data overlap
1100 | Steffen LM, Yi SY, Duprez D, Zhou X, Shikany JM, Jacobs DR, Jr. Walnut consumption and cardiac phenotypes: The Coronary Artery Risk Development in Young Adults (CARDIA) study. Nutr Metab Cardiovasc Dis. Jan 4 2021;31(1):95–101. doi:10.1016/j.numecd.2020.09.001 33097410 | Intervention or Exposure
1101 | Steger FL, Jamshed H, Martin CK, Impact of early time-restricted eating on diet quality, meal frequency, appetite, and eating behaviors: A randomized trial. Obesity (Silver Spring). Feb 2023;31 Suppl 1(Suppl 1):127–138. doi:10.1002/oby.23642 36575143 | Intervention or Exposure
1102 | Steinberg D, Kay M, Burroughs J, Svetkey LP, Bennett GG. The Effect of a Digital Behavioral Weight Loss Intervention on Adherence to the Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern in Medically Vulnerable Primary Care Patients: Results from a Randomized Controlled Trial. Journal Article; Randomized Controlled Trial; Research Support, N.I.H., Extramural. J Acad Nutr Diet. Apr 2019;119(4):574–584. doi:10.1016/j.jand.2018.12.011 30905430 | Study design; Size or Power
1103 | Sterling SR, Bowen SA. Effect of a Plant-based Intervention Among Black Individuals in the Deep South: A Pilot Study. Article in Press. J Nutr Educ Behav. Jan 2023;55(1):68–76. doi:10.1016/j.jneb.2022.08.013 36333197 | Study design; Comparator
1104 | Straczek K, Horodnicka-Jozwa A, Szmit-Domagalska J, Familial dietary intervention in children with excess body weight and its impact on eating habits, anthropometric and biochemical parameters. Front Endocrinol (Lausanne). 2022;13:1034148. doi:10.3389/fendo.2022.1034148 36531483 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
1105 | Strathearn L, Kacar HK, Avery A. Changes in dietary patterns when females engage in a weight management programme and their ability to meet Scientific Advisory Committee on Nutrition's fibre and sugar recommendations. Public Health Nutr. Aug 2020;23(12):2189–2198. doi:10.1017/S1368980019004762 32657265 | Size or Power
1106 | Stroia CM, Vranceanu M, De Lorenzo D, Grimaldi K. Could gluten free diet improve weight loss in HLA DQ2 or D8 positive subjects? Journal: Conference Abstract. Lifestyle genomics. 2021;14(4):143–144. | Publication status
1107 | Struijk EA, Hagan KA, Fung TT, Hu FB, Rodriguez-Artalejo F, Lopez-Garcia E. Diet quality and risk of frailty among older women in the Nurses' Health Study. Am J Clin Nutr. Apr 1 2020;111(4):877–883. doi:10.1093/ajcn/nqaa028 32091575 | Outcome
1108 | Su J, Geng H, Chen L, Association of healthy lifestyle with incident cardiovascular diseases among hypertensive and normotensive Chinese adults. Front Cardiovasc Med. 2023;10:1046943. doi:10.3389/fcvm.2023.1046943 36937945 | Outcome; Country
1109 | Su X, Zhu W, Li N, Adjusting DBI-2016 to dietary balance index for Chinese maternal women and assessing the association between maternal dietary quality and postpartum weight retention: A longitudinal study. PLoS One. 2020;15(8):e0237225. doi: 10.1371/journal.pone.0237225 32817619 | Comparator
1110 | Suarez-Martinez C, Yague-Guirao G, Santaella-Pascual M, Adherence to the Mediterranean Diet and Determinants Among Pregnant Women: The NELA Cohort. Nutrients. Apr 10 2021;13(4)doi:10.3390/nu13041248 | Outcome
1111 | Subhan FB, Chan CB. Diet quality and risk factors for cardiovascular disease among South Asians in Alberta. Article. Applied physiology, nutrition, and metabolism = Physiologie appliquee, nutrition et metabolisme. 2019;44(8):886–893.31172794 | Study design; Outcome
1112 | Suikki T, Maukonen M, Partonen T, Jousilahti P, Kanerva N, Mannisto S. Association between social jet lag, quality of diet and obesity by diurnal preference in Finnish adult population. Chronobiol Int. May 2021;38(5):720–731. doi: 10.1080/07420528.2021.1876721 33557623 | Study design
1113 | Suliga E, Brola W, Sobas K, Dietary Patterns and Metabolic Disorders in Polish Adults with Multiple Sclerosis. Article. Nutrients. May 4 2022;14(9)doi:10.3390/nu14091927 | Health Status
1114 | Suliga E, Ciesla E, Michel S, Diet Quality Compared to the Nutritional Knowledge of Polish, German, and Slovakian University Students-Preliminary Research. Int J Environ Res Public Health. Dec 4 2020;17(23)doi:10.3390/ijerph17239062 | Study design
1115 | Summer SS, Jenkins T, Inge T, Deka R, Khoury JC. Association of diet quality, physical activity, and abdominal obesity with metabolic syndrome z-score in black and white adolescents in the US. Nutr Metab Cardiovasc Dis. Feb 2022;32(2):346–354. doi:10.1016/j.numecd.2021.10.021 34953632 | Study design
1116 | Sun J, Buys NJ, Hills AP. Dietary pattern and its association with the prevalence of obesity, hypertension and other cardiovascular risk factors among Chinese older adults. Article. Int J Environ Res Public Health. Apr 10 2014;11(4):3956–71. doi:10.3390/ijerph110403956 24727356 | Study design
1117 | Sun J, Ruan Y, Xu N, The effect of dietary carbohydrate and calorie restriction on weight and metabolic health in overweight/obese individuals: a multi-center randomized controlled trial. Article. BMC Med. May 24 2023;21(1):192. doi:10.1186/s12916-023-02869-9 37226271 | Intervention or Exposure - Foods/Beverages Not Reported
1118 | Sun Y, Chen S, Zhao X, Adherence to the dietary approaches to stop hypertension diet and non-alcoholic fatty liver disease. Liver Int. Apr 2022;42(4):809–819. doi:10.1111/liv.15156 34990079 | Outcome; Country
1119 | Suparyatmo JB, Prayitno A. The effect of nutrition education on body mass index, waist circumference, mid-upper arm circumference and blood pressure in obese adolescents. Electronic Journal of General Medicine. 2020;17(5). doi: 10.29333/ejgm/7884 | Intervention or Exposure
1120 | Szczepanik M, Malesza IJ, Bajerska J, Energy-restricted Central-European diet stimulates liver microsomal function in obese postmenopausal women - a randomized nutritional trial with a comparison to energy-restricted Mediterranean diet. Eur Rev Med Pharmacol Sci. Nov 2020;24(21):11165–11171. doi:10.26355/eurrev_202011_23604 33215434 | Duration of Intervention; Outcome
1121 | Taetzsch A, Roberts SB, Gilhooly CH, Food cravings: Associations with dietary intake and metabolic health. Appetite. Sep 1 2020;152:104711. doi:10.1016/j.appet.2020.104711 32283186 | Study design; Intervention or Exposure
1122 | Tagliamonte S, Laiola M, Ferracane R, Vitale M, Ercolini D, Vitaglione P. Mediterranean diet consumption affects the endocannabinoid system and Akkermansia muciniphila gut levels in overweight and obese subjects. Nutrition, Metabolism & Cardiovascular Diseases. 2021;31 (11):3255–3255. | Publication status
1123 | Taheri E, Bostick RM, Hatami B, Dietary and Lifestyle Inflammation Scores Are Inversely Associated with Metabolic---Associated Fatty Liver Disease among Iranian Adults: A Nested Case-Control Study. J Nutr. Feb 8 2022;152(2):559–567. doi: 10.1093/jn/nxab391 34791370 | Outcome
1124 | Tahir MJ, Haapala JL, Foster LP, Higher maternal diet quality during pregnancy and lactation is associated with lower infant weight-for-length, body fat percent, and fat mass in early postnatal life. Article. Nutrients. 2019;11(3) | Did not account for at least 1 key confounder
1125 | Talib SH, Kabra A, Bhattu S, Ali SA, Pranita B, Sachin P. Efficacy Of DNA-based Customised Diet and Exercise Plan for Weight Management. Article. Journal, Indian Academy of Clinical Medicine. 2022;23(3–4):91–94. | Intervention or Exposure
1126 | Tang X, Andres A, West DS, Lou X, Krukowski RA. Eating behavior and weight gain during pregnancy. Article. Eat Behav. Jan 2020;36:101364. doi:10.1016/j.eatbeh.2020.101364 32032810 | Intervention or Exposure
1127 | Taniguchi T, Haslam A, Sun W, Sisk M, Hayman J, Jernigan VBB. Impact of a Farm-to-School Nutrition and Gardening Intervention for Native American Families from the FRESH Study: A Randomized Wait-List Controlled Trial. Article. Nutrients. Jun 23 2022;14(13)doi:10.3390/nu14132601 | Intervention or Exposure
1128 | Tanner H, Barrett HL, Callaway LK, Wilkinson SA, Dekker Nitert M. Consumption of a Low Carbohydrate Diet in Overweight or Obese Pregnant Women Is Associated with Longer Gestation of Pregnancy. Article. Nutrients. Oct 5 2021;13(10)doi: 10.3390/nu13103511 | Intervention or Exposure - Foods/Beverages Not Reported
1129 | Tapsell L, Neale E, Ndanuko R, Charlton K, Batterham M. International Congress of Dietetics, 1–3 September 2021, Abstract Bo Journal article; Conference proceeding. South African Journal of Clinical Nutrition. 2021;34(3):A1–A203. doi: 10.1080/16070658.2021.1968126 | Intervention or Exposure; Publication status
1130 | Taverno Ross SE, Militello G, Dowda M, Pate RR. Changes in Diet Quality in Youth Living in South Carolina From Fifth to 11th Grade. J Nutr Educ Behav. Oct 2020;52(10):928–934. doi:10.1016/j.jneb.2020.03.001 32334976 | Outcome
1131 | Tay ME, Foster E, Stevenson L, Brownlee I. The Adherence of Singaporean Students in Different Educational Institutions to Nati Food-Based Dietary Guidelines. Nutrients. Sep 30 2020;12(10)doi:10.3390/nu12102995 | Study design
1132 | Taylor CM, Doerner R, Northstone K, Kordas K. Maternal Diet During Pregnancy and Blood Cadmium Concentrations in an Observational Cohort of British Women. Article. Nutrients. Mar 26 2020;12(4)doi:10.3390/nu12040904 | Outcome
1133 | Taylor R, Rollo ME, Baldwin JN, Evaluation of a Type 2 diabetes risk reduction online program for women with recent gestational diabetes: a randomised trial. Int J Behav Nutr Phys Act. Mar 28 2022;19(1):35. doi: 10.1186/s12966-022-01275-3 35346229 | Intervention or Exposure; Comparator
1134 | Teixeira JA, Hoffman DJ, Castro TG, Pre-pregnancy dietary pattern is associated with newborn size: results from ProcriAr study. British Journal of Nutrition. 2021;126(6):903–912.33256857 | Outcome
1135 | Teo PS, van Dam RM, Whitton C, Tan LWL, Forde CG. Consumption of Foods With Higher Energy Intake Rates is Associated With Greater Energy Intake, Adiposity, and Cardiovascular Risk Factors in Adults. Article. J Nutr. Feb 1 2021;151(2):370–378. doi: 10.1093/jn/nxaa344 33244595 | Intervention or Exposure
1136 | Teo SM, Murrin CM, Mehegan J, Associations between maternal dietary scores during early pregnancy with placental outcomes. Front Nutr. Feb 8 2023;10 doi:ARTN 1060709 | Outcome
1137 | Tertsunen HM, Hantunen S, Tuomainen TP, Virtanen JK. Adherence to a healthy Nordic diet and risk of type 2 diabetes among mer the Kuopio Ischaemic Heart Disease Risk Factor Study. Article. Eur J Nutr. Oct 2021;60(7):3927–3934. doi:10.1007/s00394-021-02569-1 33904995 | Outcome
1138 | Tessari S, Casazza M, De Boni G, Promoting health and preventing non-communicable diseases: evaluation of the adherence of the Italian population to the Mediterranean Diet by using the PREDIMED questionnaire. Ann Ig. Jul-Aug 2021;33(4):337–346. doi: 10.7416/ai.2020.2393 33270077 | Study design
1139 | Tettamanzi F, Bagnardi V, Louca P, A High Protein Diet Is More Effective in Improving Insulin Resistance and Glycemic Variability Compared to a Mediterranean Diet-A Cross-Over Controlled Inpatient Dietary Study. Article. Nutrients. Dec 7 2021;13(12)doi:10.3390/nu13124380 | Duration of Intervention
1140 | Teymoori F, Jahromi MK, Ahmadirad H, The association of dietary and lifestyle indices for insulin resistance with the risk of cardiometabolic diseases among Iranian adults. Scientific Reports. Apr 17 2023;13(1)doi:ARTN 6224 | Intervention or Exposure; Country
1141 | Teymoori F, Mokhtari E, Jahromi MK, Dietary and lifestyle indices for hyperinsulinemia with the risk of obesity phenotypes: a prospective cohort study among Iranian adult population. Bmc Public Health. May 16 2022;22(1)doi:ARTN 990 | Outcome
1142 | Thi Nguyen NT, Tang HK, Nguyen MN, Dibley MJ, Alam NA. Effect of a peer-led education intervention on dietary behaviour and physical activity among adolescents in Ho Chi Minh City, Vietnam: a pilot study. Eur J Clin Nutr. Nov 2022;76(11):1590–1593. doi:10.1038/s41430-022-01140-3 35411029 | Intervention or Exposure
1143 | Thomas MS, Puglisi M, Malysheva O, Eggs Improve Plasma Biomarkers in Patients with Metabolic Syndrome Following a Plant-Based Diet-A Randomized Crossover Study. Article. Nutrients. May 20 2022;14(10)doi:10.3390/nu14102138 | Intervention or Exposure; Duration of Intervention
1144 | Thompson AL, Jahnke JR, Teran E, Bentley ME. Pathways linking maternal mental health and child health in a dual burden context: Evidence from Galapagos, Ecuador. Soc Sci Med. Jul 2022;305:115043. doi:10.1016/j.socscimed.2022.115043 35660699 | Intervention or Exposure
1145 | Thompson AS, Tresserra-Rimbau A, Karavasiloglou N, Association of Healthful Plant-based Diet Adherence With Risk of Mortality and Major Chronic Diseases Among Adults in the UK. Jama Network Open. Mar 2023;6(3)doi:ARTN e234714 | Outcome
1146 | Thorndike AN, McCurley JL, Gelsomin ED, Automated Behavioral Workplace Intervention to Prevent Weight Gain and Improve Diet: The ChooseWell 365 Randomized Clinical Trial. JAMA Netw Open. Jun 1 2021;4(6):e2112528. doi: 10.1001/jamanetworkopen.2021.12528 34097048 | Comparator
1147 | Timmermans S, Steegers-Theunissen RP, Vujkovic M, Major dietary patterns and blood pressure patterns during pregnancy: the Generation R Study. Am J Obstet Gynecol. Oct 2011;205(4):337 e1–12. doi: 10.1016/j.ajog.2011.05.013 | Outcome
1148 | Tomaino L, Reyes Suarez D, Reyes Dominguez A, Garcia Cruz LM, Ramos Diaz M, Serra Majem L. Adherence to Mediterranean diet is not associated with birthweight - Results form a sample of Canarian pregnant women. Nutr Hosp. Feb 17 2020;37(1):86–92. La adherencia a la dieta mediterranea no se asocia al peso al nacer: resultados de una muestra de mujeres canarias embarazadas. doi: 10.20960/nh.02780 31876428 | Study design
1149 | Tomlinson DJ, Erskine RM, Morse Cl, Onambele GL. Body fat percentage, body mass index, fat mass index and the ageing bone: Their singular and combined roles linked to physical activity and diet. Article. Nutrients. 2019; 11(1) | Study design; Intervention or Exposure
1150 | Tong EH, Lai JS, Whitton C, Changes in Diet Quality from Mid- to Late Life Are Associated with Cognitive Impairment in the Singapore Chinese Health Study. Article. J Nutr. Sep 4 2021;151(9):2800–2807. doi:10.1093/jn/nxab179 34049404 | Outcome
1151 | Tong TYN, Appleby PN, Bradbury KE, Risks of ischaemic heart disease and stroke in meat eaters, fish eaters, and vegetarians over 18 years of follow-up: results from the prospective EPIC-Oxford study. Article. BMJ. Sep 4 2019;366:I4897. doi:10.1136/bmj.l4897 | Outcome
1152 | Tosi M, Matelloni IA, Mancini M, Multiple beneficial effects of 1-year nutritional-behavioral intervention on anthropometric and metabolic parameters in overweight and obese boys. J Endocrinol Invest. Nov 2023;46(11):2331–2342. doi:10.1007/s40618-023-02088-2 37069323 | Study design
1153 | Trichia E, Luben R, Khaw K-T, Wareham NJ, Imamura F, Forouhi NG. The associations of longitudinal changes in consumption of total and types of dairy products and markers of metabolic risk and adiposity: findings from the European Investigation into Cancer and Nutrition (EPIC)-Norfolk study, United Kingdom. American Journal of Clinical Nutrition. 2020; 111(5):1018–1026.31915813 | Intervention or Exposure
1154 | Tripp ML, Dahlberg CJ, Eliason S, A Low-Glycemic, Mediterranean Diet and Lifestyle Modification Program with Targeted Nutraceuticals Reduces Body Weight, Improves Cardiometabolic Variables and Longevity Biomarkers in Overweight Subjects: A 13-Week Observational Trial. Article. J Med Food. May 2019;22(5):479–489. doi:10.1089/jmf.2018.0063 31084538 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
1155 | Truche AS, Bailly S, Fabre O, Legrand R, Zaoui P. A Specific High-Protein Weight Loss Program Does Not Impair Renal Function in Patients Who Are Overweight/Obese. Article. Nutrients. Jan 17 2022;14(2)doi:10.3390/nu14020384 | Outcome; Comparator
1156 | Tsaban G, Bilitzky-Kopit A, Yaskolka Meir A, The Effect of Weight-Loss Interventions on Cervical and Chin Subcutaneous Fat Depots; the CENTRAL Randomized Controlled Trial. Article. Nutrients. Oct 27 2021;13(11)doi:10.3390/nu13113827 | Intervention or Exposure
1157 | Tsaban G, Yaskolka Meir A, Rinott E, The effect of green Mediterranean diet on cardiometabolic risk; a randomised controlled trial. Heart. Jun 11 2021;107(13):1054–1061. doi:10.1136/heartjnl-2020-317802 33234670 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
1158 | Tsai MC, Yeh TL, Hsu HY, Comparison of four healthy lifestyle scores for predicting cardiovascular events in a national cohort study. Sci Rep. Nov 12 2021;11(1):22146. doi:10.1038/s41598-021-01213-6 34772956 | Outcome; Country
1159 | Tsakoumaki F, Kyrkou C, Fotiou M, Framework of Methodology to Assess the Link between A Posteriori Dietary Patterns and Nutritional Adequacy: Application to Pregnancy. Article. Metabolites. Apr 27 2022;12(5)doi:10.3390/metabo12050395 | Outcome
1160 | Tsoi KY, Chan RSM, Li LS, Evaluation of dietary pattern in early pregnancy using the FIGO Nutrition Checklist compared to a food frequency questionnaire. Int J Gynaecol Obstet. Sep 2020;151 Suppl 1(Suppl 1):37–44. doi:10.1002/ijgo.13324 32894588 | Did not account for at least 1 key confounder
1161 | Tsuzaki J, Maskarinec G, Mapa V, Diet Quality and Body Mass Index Over 20 Years in the Multiethnic Cohort. J Acad Nutr Diet. Feb 2024;124(2):194–204. doi:10.1016/j.jand.2023.02.001 36758897 | Study design
1162 | Tunçer E, Keser A, Nüket Ünsal E, Odabaşı Güneş S, Akın O. The Correlation Between Adherence to Mediterranean Diet and HOMA-IR in Children and Adolescents. Article. Güncel Pediatri. 2022;20(2):188–196. doi:10.4274/jcp.2022.59251 | Study design
1163 | Turner-McGrievy GM, Wilcox S, Frongillo EA, Effect of a Plant-Based vs Omnivorous Soul Food Diet on Weight and Lipid Levels Among African American Adults: A Randomized Clinical Trial. Jama Network Open. Jan 12 2023;6(1)doi:ARTN e2250626 | Intervention or Exposure - Foods/Beverages Not Reported
1164 | Turner-McGrievy GM, Wilson MJ, Carswell J, A 12-Week Randomized Intervention Comparing the Healthy US, Mediterranean, and Vegetarian Dietary Patterns of the US Dietary Guidelines for Changes in Body Weight, Hemoglobin A1c, Blood Pressure, and Dietary Quality among African American Adults. Journal of Nutrition. Feb 2023;153(2):579–587. doi: 10.1016/j.tjnut.2022.11.020 36894249 | Intervention or Exposure
1165 | Tzenios N, Lewis ED, Crowley DC, Chahine M, Evans M. Examining the Efficacy of a Very-Low-Carbohydrate Ketogenic Diet on Cardiovascular Health in Adults with Mildly Elevated Low-Density Lipoprotein Cholesterol in an Open-Label Pilot Study. Article. Metab Syndr Relat Disord. Mar 2022;20(2):94–103. doi:10.1089/met.2021.0042 34918971 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
1166 | Ulven SM, Holven KB, Rundblad A, An Isocaloric Nordic Diet Modulates RELA and TNFRSF1A Gene Expression in Peripheral Blood Mononuclear Cells in Individuals with Metabolic Syndrome-A SYSDIET Sub-Study. Article. Nutrients. Dec 3 2019;11(12)doi:10.3390/nu11122932 | Outcome
1167 | Umemoto S, Onaka U, Kawano R, Effects of a Japanese Cuisine-Based Antihypertensive Diet and Fish Oil on Blood Pressure and Its Variability in Participants with Untreated Normal High Blood Pressure or Stage I Hypertension: A Feasibility Randomized Controlled Study. Article. J Atheroscler Thromb. Feb 1 2022;29(2):152–173. doi: 10.5551/jat.57802 33298663 | Duration of Intervention
1168 | Ushula TW, Mamun A, Darssan D, Dietary patterns and the risk of abnormal blood lipids among young adults: A prospective cohort study. Article. Nutr Metab Cardiovasc Dis. May 2022;32(5):1165–1174. doi:10.1016/j.numecd.2022.01.030 35260316 | Outcome
1169 | Ushula TW, Mamun A, Darssan D, Dietary patterns and the risks of metabolic syndrome and insulin resistance among young adults: Evidence from a longitudinal study. Clinical Nutrition. Jul 2022;41(7):1523–1531. doi:10.1016/j.clnu.2022.05.006 35667268 | Size or Power
1170 | Ushula TW, Mamun A, Darssan D, Dietary patterns and young adult body mass change: A 9-year longitudinal study. Eur J Nutr. Jun 2023;62(4):1657–1666. doi:10.1007/s00394-023-03101-3 36763149 | Size or Power
1171 | Vaitkeviciute J, Petrauskiene A. The Associations between Body Mass Index of Seven- and Eight-Year-Old Children, Dietary Behaviour and Nutrition-Related Parenting Practices. Article. Medicina (Kaunas, Lithuania). 2019;55(1) | Study design
1172 | Valentini DF, Jr., Fernandes D, Campos VJ, Mazzini GS, Gurski RR. Dietary weight loss intervention provides improvement of gastroesophageal reflux disease symptoms-A randomized clinical trial. Clin Obes. Feb 2023;13(1):e12556. doi: 10.1111/cob.12556 36151602 | Intervention or Exposure
1173 | van de Pas KGFI, Lubrecht JW, Hesselink ML, Winkens B, van Dielen FMH, Vreugdenhil ACE. The Effect of a Multidisciplinary Lifestyle Intervention on Health Parameters in Children versus Adolescents with Severe Obesity. Article. Nutrients. Apr 25 2022;14(9)doi:10.3390/nu14091795 | Study design; Intervention or Exposure
1174 | van Dijk MR, Koster MPH, Oostingh EC, Willemsen SP, Steegers EAP, Steegers-Theunissen RPM. A mobile app lifestyle intervention to improve healthy nutrition in women before and during early pregnancy: Single-center randomized controlled trial. Article. Journal of Medical Internet Research. 2020;22(5) | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
1175 | van Elten TM, Karsten MDA, Geelen A, Preconception lifestyle intervention reduces long term energy intake in women with obesity and infertility: a randomised controlled trial. Journal Article; Multicenter Study; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Int J Behav Nutr Phys Act. Jan 8 2019;16(1):3. doi:10.1186/s12966-018-0761-6 30621789 | Intervention or Exposure; Outcome
1176 | Vandyousefi S, Davis JN, Gunderson EP. Association of infant diet with subsequent obesity at 2–5 years among children exposed to gestational diabetes: the SWIFT study. Diabetologia. May 2021;64(5):1121–1132. doi:10.1007/s00125-020-05379-y 33495846 | Intervention or Exposure
1177 | Vaughn AE, Hennink-Kaminski H, Moore R, Evaluating a child care-based social marketing approach for improving children's diet and physical activity: results from the Healthy Me, Healthy We cluster-randomized controlled trial. Transl Behav Med. Apr 7 2021;11(3):775–784. doi:10.1093/tbm/ibaa113 33231679 | Intervention or Exposure
1178 | Velluzzi F, Anedda J, Pisanu S, Mediterranean diet, lifestyle and quality of life in Sardinian patients affected with Hidradenitis suppurativa. J Public Health Res. Nov 29 2021;11(2)doi:10.4081/jphr.2021.2706 | Study design; Health Status
1179 | Velluzzi F, Deledda A, Lombardo M, Application of Artificial Neural Networks (ANN) to Elucidate the Connections among Smell, Obesity with Related Metabolic Alterations, and Eating Habit in Patients with Weight Excess. Metabolites. Feb 2023;13(2)doi:ARTN 206 | Study design
1180 | Verde L, Dalamaga M, Capo X, The Antioxidant Potential of the Mediterranean Diet as a Predictor of Weight Loss after a Very Low-Calorie Ketogenic Diet (VLCKD) in Women with Overweight and Obesity. Antioxidants-Basel. Jan 2023;12(1)doi:ARTN 18 | Intervention or Exposure; Duration of Intervention
1181 | Verduci E, Vizzuso S, Ippolito G, Effectiveness of individual vs. group-based lifestyle intervention on anthropometric and metabolic profile of obese children. Journal: Conference Abstract. Journal of pediatric gastroenterology and nutrition. 2019;68:1020-. | Publication status
1182 | Vergara M, Hauser ME, Aronica L, Associations of Changes in Blood Lipid Concentrations with Changes in Dietary Cholesterol Intake in the Context of a Healthy Low-Carbohydrate Weight Loss Diet: A Secondary Analysis of the DIETFITS Trial. Article. Nutrients. Jun 4 2021;13(6)doi: 10.3390/nu13061935 | Study design; Intervention or Exposure
1183 | Vidal-Ostos F, Ramos-Lopez O, Jebb SA, Dietary protein and the glycemic index handle insulin resistance within a nutritional program for avoiding weight regain after energy-restricted induced weight loss. Article. Nutr Metab (Lond). Oct 19 2022;19(1):71. doi:10.1186/s12986-022-00707-y 36261843 | Intervention or Exposure - Foods/Beverages Not Reported
1184 | Vilela S, Oliveira A, Severo M, Lopes C. Chrono-Nutrition: The Relationship between Time-of-Day Energy and Macronutrient Intake and Children's Body Weight Status. Article. Journal of biological rhythms. 2019;34(3):332–342.30917726 | Intervention or Exposure
1185 | Villano I, La Marra M, Messina A, Effects of vegetarian and vegan nutrition on body composition in competitive futsal athletes. Article. Progress in Nutrition. 2021;23(2) | Intervention or Exposure - Foods/Beverages Not Reported
1186 | Vitale M, Giacco R, Laiola M, Acute and chronic improvement in postprandial glucose metabolism by a diet resembling the traditional Mediterranean dietary pattern: Can SCFAs play a role? Clin Nutr. Feb 2021;40(2):428–437. doi:10.1016/j.clnu.2020.05.025 32698959 | Duration of Intervention
1187 | von Ruesten A, Brantsaeter AL, Haugen M, Adherence of pregnant women to Nordic dietary guidelines in relation to postpartum weight retention: results from the Norwegian Mother and Child Cohort Study. BMC Public Health. Jan 24 2014;14:75. doi:10.1186/1471-2458-14-75 24456804 | Outcome
1188 | Voortman T, Chen ZL, Girschik C, Kavousi M, Franco OH, Braun KVE. Associations between macronutrient intake and coronary heart disease (CHD): The Rotterdam Study. Clinical Nutrition. Nov 2021;40(11):5494–5499. doi:10.1016/j.clnu.2021.08.022 34656031 | Intervention or Exposure
1189 | Voorwinde V, Hoekstra T, Monpellier VM, Steenhuis IHM, Janssen IMC, van Stralen MM. Five-year weight loss, physical activity, and eating style trajectories after bariatric surgery. Surg Obes Relat Dis. Jul 2022;18(7):911–918. doi:10.1016/j.soard.2022.03.020 35618645 | Intervention or Exposure; Health Status- 100% Hospitalized/Surgical
1190 | Vucic Lovrencic M, Geric M, Kosuta I, Dragicevic M, Garaj-Vrhovac V, Gajski G. Sex-specific effects of vegetarian diet on adiponectin levels and insulin sensitivity in healthy non-obese individuals. Nutrition. Nov-Dec 2020;79–80:110862. doi:10.1016/j.nut.2020.110862 | Study design
1191 | Wachsmuth NB, Aberer F, Haupt S, The Impact of a High-Carbohydrate/Low Fat vs. Low-Carbohydrate Diet on Performance and Body Composition in Physically Active Adults: A Cross-Over Controlled Trial. Article. Nutrients. Jan 18 2022;14(3)doi:10.3390/nu14030423 | Duration of Intervention
1192 | Wade AT, Davis CR, Dyer KA, Hodgson JM, Woodman RJ, Murphy KJ. Effects of Mediterranean diet supplemented with lean pork on blood pressure and markers of cardiovascular risk: findings from the MedPork trial. Br J Nutr. Oct 28 2019;122(8):873–883. doi:10.1017/S0007114519001168 31177999 | Duration of Intervention
1193 | Wadolowska L, Hamulka J, Kowalkowska J, Changes in Sedentary and Active Lifestyle, Diet Quality and Body Composition Nine Months after an Education Program in Polish Students Aged 11 (-)12 Years: Report from the ABC of Healthy Eating Study. Controlled Clinical Trial; Journal Article. Nutrients. Feb 3 2019; 11(2)doi:10.3390/nu11020331 | Intervention or Exposure; Comparator
1194 | Wagner S, Lioret S, Girerd N, Association of Dietary Patterns Derived Using Reduced-Rank Regression With Subclinical Cardiovascular Damage According to Generation and Sex in the STANISLAS Cohort. Article. J Am Heart Assoc. Apr 7 2020;9(7):e013836. doi:10.1161/JAHA.119.013836 32200718 | Outcome
1195 | Walsh El, Jacka FN, Butterworth P, Anstey KJ, Cherbuin N. Midlife susceptibility to the effects of poor diet on diabetes risk. Eur J Clin Nutr. Jan 2021;75(1):85–90. doi:10.1038/s41430-020-0673-9 32651462 | Outcome
1196 | Walton K, McGee M, Sato J, Social-emotional functioning and dietary intake among children born with a very low birth weight. Appl Physiol Nutr Me. Jul 2022;47(7):737–748. doi:10.1139/apnm-2021-0434 | Study design; Health Status
1197 | Wan Y, Wang F, Yuan J, Effects of dietary fat on gut microbiota and faecal metabolites, and their relationship with cardiometabolic risk factors: a 6-month randomised controlled-feeding trial. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Gut. 2019;68(8):1417–1429.30782617 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
1198 | Wang H, Herforth AW, Xi B, Zou Z. Validation of the Diet Quality Questionnaire in Chinese Children and Adolescents and Relationship with Pediatric Overweight and Obesity. Nutrients. Aug 29 2022;14(17)doi:10.3390/nu14173551 | Study design
1199 | Wang H, Wang Y, Shi Z, Association between Dietary Patterns and Metabolic Syndrome and Modification Effect of Altitude: A Cohort Study of Tibetan Adults in China. Article. Nutrients. May 8 2023;15(9)doi:10.3390/nu15092226 | Size or Power
1200 | Wang HZ, Huang L, Lin LX, The overall plant-based diet index during pregnancy and risk of gestational diabetes mellitus: a prospective cohort study in China. British Journal of Nutrition. Nov 28 2021;126(10):1519–1528. doi:Pii S0007114521000234 33468274 | Outcome
1201 | Wang XM, Zhong WF, Li ZH, Dietary diversity and frailty among older Chinese people: evidence from the Chinese Longitudinal Healthy Longevity Study. Article. Am J Clin Nutr. Feb 2023;117(2):383–391. doi: 10.1016/j.ajcnut.2022.11.017 36811562 | Outcome
1202 | Wang Y, Luo BR, Xiang J. The association between soy intake and risk of gestational diabetes mellitus: a prospective cohort study. Bmc Pregnancy and Childbirth. Oct 13 2021;21(1)doi:ARTN 695 | Intervention or Exposure
1203 | Wang Y, Su X, Chen Y, Unfavorable Dietary Quality Contributes to Elevated Risk of Ischemic Stroke among Residents in Southwest China: Based on the Chinese Diet Balance Index 2016 (DBI-16). Article. Nutrients. Feb 7 2022;14(3)doi:10.3390/nu14030694 | Outcome
1204 | Wang Y, Wang K, Du M, Maternal consumption of ultra-processed foods and subsequent risk of offspring overweight or obesity: results from three prospective cohort studies. BMJ. Oct 5 2022;379:e071767. doi:10.1136/bmj-2022-071767 36198411 | Outcome
1205 | Wang YB, Shivappa N, Hebert JR, Page AJ, Gill TK, Melaku YA. Association between Dietary Inflammatory Index, Dietary Patterns, Plant-Based Dietary Index and the Risk of Obesity. Article. Nutrients. May 2 2021;13(5)doi:10.3390/nu13051536 | Size or Power
1206 | Wang YY, Chen B, Zhang JW, Diets with higher insulinaemic potential are associated with increased risk of overall and cardiovascular disease-specific mortality. British Journal of Nutrition. Nov 28 2022;128(10):2011–2020. doi:Pii S0007114521004815 34863319 | Outcome
1207 | Wang YY, Tian T, Pan D, The relationship between dietary patterns and overweight and obesity among adult in Jiangsu Province of China: a structural equation model. BMC Public Health. Jun 25 2021;21(1):1225. doi: 10.1186/s12889-021-11341-3 34172040 | Country
1208 | Wang Z, Groen H, Cantineau AEP, Effectiveness of a 6-Month Lifestyle Intervention on Diet, Physical Activity, Quality of Life, and Markers of Cardiometabolic Health in Women with PCOS and Obesity and Non-PCOS Obese Controls: One Size Fits All? Nutrients. Sep 28 2021;13(10)doi:10.3390/nu13103425 | Intervention or Exposure; Comparator
1209 | Wang Z, Zhao S, Cui X, Effects of Dietary Patterns during Pregnancy on Preterm Birth: A Birth Cohort Study in Shanghai. Article. Nutrients. Jul 10 2021;13(7)doi:10.3390/nu13072367 | Outcome
1210 | Ward SJ, Hill AM, Buckley JD, Minimal changes in telomere length after a 12-week dietary intervention with almonds in mid-age to older, overweight and obese Australians: results of a randomised clinical trial. Br J Nutr. Mar 28 2022;127(6):872–884. doi:10.1017/S0007114521001549 33971995 | Outcome; Comparator
1211 | Watanabe D, Murakami H, Gando Y, Association Between Temporal Changes in Diet Quality and Concurrent Changes in Dietary Intake, Body Mass Index, and Physical Activity Among Japanese Adults: A Longitudinal Study. Front Nutr. Feb 8 2022;9 doi:ARTN 753127 | Intervention or Exposure - Foods/Beverages Not Reported
1212 | Waterplas J, Versele V, D'Hondt E, A 10-year longitudinal study on the associations between changes in plant-based diet indices, anthropometric parameters and blood lipids in a Flemish adult population. Nutr Diet. Apr 2020;77(2):196–203. doi:10.1111/1747-0080.12578 31495999 | Size or Power
1213 | Watson A, Maher C, Golley R, Children's activity and diet behaviours in the summer holidays versus school year. Pediatr Obes. Jul 2023;18(7):e13029. doi:10.1111/ijpo.13029 36945145 | Study design; Outcome
1214 | Webster J, Greenwood DC, Cade JE. Risk of hip fracture in meat-eaters, pescatarians, and vegetarians: results from the UK Women's Cohort Study. BMC Med. Aug 11 2022;20(1):275. doi:10.1186/s12916-022-02468-0 35948956 | Intervention or Exposure - Foods/Beverages Not Reported; Outcome
1215 | Wei L, Fan J, Dong R, The Effect of Dietary Pattern on Metabolic Syndrome in a Suburban Population in Shanghai, China. Article. Nutrients. May 4 2023;15(9)doi:10.3390/nu15092185 | Study design; Outcome
1216 | Wei X, He JR, Lin Y, The influence of maternal dietary patterns on gestational weight gain: A large prospective cohort study in China. Article. Nutrition. Mar 2019;59:90–95. doi: 10.1016/j.nut.2018.07.113 30471529 | Data overlap
1217 | Weigensberg MJ, Avila Q, Spruijt-Metz D, Imagine HEALTH: Randomized Controlled Trial of a Guided Imagery Lifestyle Intervention to Improve Obesity-Related Lifestyle Behaviors in Predominantly Latinx Adolescents. Article. J Altern Complement Med. Sep 2021;27(9):738–749. doi:10.1089/acm.2020.0515 34037459 | Intervention or Exposure; Comparator
1218 | White SL, Flynn AC, Poston L. Impact of a positive or negative diagnosis of gestational diabetes and treatment, on weight change and dietary behaviour in an obese cohort: secondary analysis of the UK pregnancies better eating and activity trial (UPBEAT) randomised controlled trial (RCT). Journal: Conference Abstract. Diabetic medicine. 2019;36:65-.30175871 | Intervention or Exposure; Outcome; Publication status
1219 | Whyte K, Contento I, Wolf R, A secondary analysis of maternal ultra-processed food intake in women with overweight or obesity and associations with gestational weight gain and neonatal body composition outcomes. J Mother Child. Dec 1 2021;25(4):244–259. doi:10.34763/jmotherandchild.20212504.d-21-00025 35325513 | Outcome
1220 | Wiertsema CJ, Mensink-Bout SM, Duijts L, Mulders A, Jaddoe VWV, Gaillard R. Associations of DASH Diet in Pregnancy With Blood Pressure Patterns, Placental Hemodynamics, and Gestational Hypertensive Disorders. J Am Heart Assoc. Jan 5 2021;10(1):e017503. doi:10.1161/JAHA.120.017503 33356384 | Outcome
1221 | Wilcox S, Liu J, Turner-McGrievy GM, Boutte AK, Wingard E. Effects of a behavioral intervention on physical activity, diet, and health-related quality of life in pregnant women with elevated weight: results of the HIPP randomized controlled trial. Int J Behav Nutr Phys Act. Dec 9 2022;19(1):145. doi:10.1186/s12966-022-01387-w 36494702 | Intervention or Exposure; Outcome
1222 | Wilkinson SA, Fjeldsoe B, Willcox JC. Evaluation of the Pragmatic Implementation of a Digital Health Intervention Promoting Healthy Nutrition, Physical Activity, and Gestational Weight Gain for Women Entering Pregnancy at a High Body Mass Index. Nutrients. Feb 2023;15(3)doi:ARTN 588 | Intervention or Exposure - Foods/Beverages Not Reported
1223 | Wilkinson SA, Schoenaker DAJM, de Jersey S, Exploring the diets of mothers and their partners during pregnancy: Findings from the Queensland Family Cohort pilot study. Nutrition & Dietetics. Nov 2022;79(5):602–615. doi:10.1111/1747-0080.12733 35355379 | Outcome; Comparator
1224 | Williams KA, Fughhi I, Fugar S, Nutrition Intervention for Reduction of Cardiovascular Risk in African Americans Using the 2019 American College of Cardiology/American Heart Association Primary Prevention Guidelines. Article. Nutrients. Sep 28 2021;13(10)doi: 10.3390/nu13103422 | Duration of Intervention
1225 | Williams LT, Collins CE, Morgan PJ, Hollis JL. Maintaining the Outcomes of a Successful Weight Gain Prevention Intervention in Mid-Age Women: Two Year Results from the 40-Something Randomized Control Trial. Journal: Article. Nutrients. May 17 2019;11(5)doi:10.3390/nu11051100 | Intervention or Exposure; Comparator
1226 | Wilson D, Driller M, Winwood P, Clissold T, Johnston B, Gill N. The Effectiveness of a Combined Healthy Eating, Physical Activity, and Sleep Hygiene Lifestyle Intervention on Health and Fitness of Overweight Airline Pilots: A Controlled Trial. Nutrients. May 9 2022;14(9)doi:10.3390/nu14091988 | Intervention or Exposure
1227 | Wilson JM, Lowery RP, Roberts MD, Effects of Ketogenic Dieting on Body Composition, Strength, Power, and Hormonal Profiles in Resistance Training Men. J Strength Cond Res. Dec 2020;34(12):3463–3474. doi:10.1519/JSC.0000000000001935 28399015 | Intervention or Exposure; Duration of Intervention
1228 | Winpenny EM, van Sluijs EMF, Forouhi NG. How do short-term associations between diet quality and metabolic risk vary with age? Article. European Journal of Nutrition. 2021;60(1):517–527.32399624 | Study design
1229 | Witkowska AM, Waskiewicz A, Zujko ME, The Consumption of Nuts is Associated with Better Dietary and Lifestyle Patterns in Polish Adults: results of WOBASZ and WOBASZ II Surveys. Journal: Article. Nutrients. 2019;11(6) | Study design; Intervention or Exposure
1230 | Wong JMW, Yu S, Ma C, Stimulated Insulin Secretion Predicts Changes in Body Composition Following Weight Loss in Adults with High BMI. Article in Press. J Nutr. Mar 3 2022;152(3):655–662. doi:10.1093/jn/nxab315 34587231 | Intervention or Exposure
1231 | Wooldridge JS, Blanco BH, Dochat C, Relationships Between Dietary Intake and Weight-Related Experiential Avoidance Following Behavioral Weight-Loss Treatment. Int J Behav Med. Feb 2022;29(1):104–109. doi:10.1007/s12529-021-09990-0 33864234 | Study design; Intervention or Exposure; Outcome
1232 | Wrottesley SV, Prioreschi A, Kehoe SH, Ward KA, Norris SA. A maternal "mixed, high sugar" dietary pattern is associated with fetal growth. Matern Child Nutr. Apr 2020;16(2):e12912. doi:10.1111/mcn.12912 31777191 | Intervention or Exposure; Outcome
1233 | Wrzosek M, Wozniak J, Wlodarek D. The effect of high-fat versus high-carb diet on body composition in strength-trained males. Food Sci Nutr. May 2021;9(5):2541–2548. doi:10.1002/fsn3.2204 34026070 | Intervention or Exposure - Foods/Beverages Not Reported
1234 | Wu L, Ouyang J, Lai Y, Combined healthy lifestyle in early pregnancy and risk of gestational diabetes mellitus: A prospective cohort study. BJOG. Dec 2023; 130(13): 1611–1619. doi:10.1111/1471-0528.17548 37212437 | Intervention or Exposure; Outcome
1235 | Wu YF, Chien KL, Chen YC. Association between genetic risk score and tri-ponderal mass index growth trajectories among different dietary consumption adolescents in a prospective Taiwanese cohort. Article. Nutr Metab (Lond). Dec 19 2022;19(1):83. doi: 10.1186/s12986-022-00718-9 36536439 | Intervention or Exposure
1236 | Xiao X, Qin Z, Lv X, Dietary patterns and cardiometabolic risks in diverse less-developed ethnic minority regions: results from the China Multi-Ethnic Cohort (CMEC) Study. Lancet Reg Health West Pac. Oct 2021;15:100252. doi:10.1016/j.lanwpc.2021.100252 34528018 | Study design; Outcome
1237 | Xing G, Huang Y, Liu X. Association between Dietary Pattern, Nutritional Status, Metabolic Factors, and Nonalcoholic Fatty Liver Disease. Contrast Media Mol Imaging. 2022;2022:4157403. doi: 10.1155/2022/4157403 35992537 | Health Status
1238 | Xiong W, Cui S, Dong J, Effect of Circadian Distribution of Energy and Macronutrients on Gestational Weight Gain in Chinese Pregnant Women. Article. Nutrients. Apr 27 2023;15(9)doi:10.3390/nu15092106 | Intervention or Exposure
1239 | Xu C, Cao Z. Cardiometabolic diseases, total mortality, and benefits of adherence to a healthy lifestyle: a 13-year prospective UK Biobank study. J Transl Med. May 19 2022;20(1):234. doi: 10.1186/s12967-022-03439-y 35590361 | Intervention or Exposure; Outcome
1240 | Xu CJ, Cao Z, Yang HX, Hou YB, Wang XH, Wang YG. Association Between the EAT-Lancet Diet Pattern and Risk of Type 2 Diabetes: A Prospective Cohort Study. Front Nutr. Jan 14 2022;8doi:ARTN 784018. doi:10.3389/fnut.2021.784018 | Outcome
1241 | Xue Q, Li X, Ma H, Changes in pedometer-measured physical activity are associated with weight loss and changes in body composition and fat distribution in response to reduced-energy diet interventions: The POUNDS Lost trial. Article in Press. Diabetes Obes Metab. Jun 2022;24(6): 1000–1009. doi:10.1111/dom.14662 35112774 | Intervention or Exposure
1242 | Xue Y, Liu C, Pang SB, The association between the dietary pattern in abdominal obesity based on visceral fat index and dyslipidaemia in the Henan Rural Cohort Study. Br J Nutr. Aug 28 2022;128(4):762–769. doi:10.1017/S0007114521003640 34511145 | Study design
1243 | Yamada P, Paetow A, Chan M, Arslan A, Landberg R, Young BK. Pregnancy outcomes with differences in grain consumption: a randomized controlled trial. J Perinat Med. May 25 2022;50(4):411–418. doi:10.1515/jpm-2021-0479 34981703 | Intervention or Exposure
1244 | Yamada S, Inoue G, Ooyane H, Nishikawa H. Changes in body weight, dysglycemia, and dyslipidemia after moderately low-carbohydrate diet education (Locabo challenge program) among workers in japan. Article. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2021;14:2863–2870.34188509 | Study design; Intervention or Exposure
1245 | Yamakawa M, Wada K, Koda S, High Intake of Free Sugars, Fructose, and Sucrose Is Associated with Weight Gain in Japanese Men. J Nutr. Feb 1 2020;150(2):322–330. doi:10.1093/jn/nxz227 31532489 | Intervention or Exposure
1246 | Yamashita T, Obara T, Yonezawa Y, Dietary patterns before and during pregnancy and small for gestational age in Japan: a prospective birth cohort study. Nutrition Journal. Sep 16 2022;21(1)doi:ARTN 57.10.1186/s12937–022-00808-7 | Outcome
1247 | Yang C, Guo QY, Cui MX, Association between maternal metabolic profiles in pregnancy, dietary patterns during lactation and breast milk leptin: a retrospective cohort study. British Journal of Nutrition. Nov 14 2023;130(9):1537–1547. doi: 10.1017/S0007114523000600 37066691 | Outcome
1248 | Yang HJ, Kim MJ, Hur HJ, Lee BK, Kim MS, Park S. Association Between Korean-Style Balanced Diet and Risk of Abdominal Obesity in Korean Adults: An Analysis Using KNHANES-VI (2013–2016). Front Nutr. Jan 20 2022;8. doi: 10.3389/fnut.2021.772347 | Study design
1249 | Yang JX, Qian F, Chavarro JE, Modifiable risk factors and long term risk of type 2 diabetes among individuals with a history of gestational diabetes mellitus: prospective cohort study. Bmj-Brit Med J. Sep 21 2022;378. doi: 10.1136/bmj-2022-070312 | Outcome
1250 | Yang X, Li Y, Wang C, Association of plant-based diet and type 2 diabetes mellitus in Chinese rural adults: The Henan Rural Cohort Study. J Diabetes Investig. Sep 2021;12(9):1569–1576. doi: 10.1111/jdi.13522 | Outcome
1251 | Yao S, Xiao S, Jin X, Effect of a community-based child health counselling intervention on health-seeking behaviours, complementary feeding and nutritional condition among children aged 6–23 months in rural China: A pre- and post-comparison study. Article. Matern Child Nutr. Jan 2022;18(1):e13289. doi:10.1111/mcn.13289 34816596 | Study design; Intervention or Exposure
1252 | Yaskolka Meir A, Rinott E, Tsaban G, Effect of green-Mediterranean diet on intrahepatic fat: the DIRECT PLUS randomised controlled trial. Gut. Nov 2021;70(11):2085–2095. doi:10.1136/gutjnl-2020-323106 33461965 | Comparator
1253 | Yasuda J, Murata K, Hasegawa T, Relationship between protein intake and resistance training-induced muscle hypertrophy in middle-aged women: A pilot study. Article. Nutrition. May 2022;97:111607. doi: 10.1016/j.nut.2022.111607 35231855 | Intervention or Exposure - Foods/Beverages Not Reported
1254 | Yee LM, Silver RM, Haas DM, Quality of periconceptional dietary intake and maternal and neonatal outcomes. Am J Obstet Gynecol. Jul 2020;223(1):121 e1–121 e8. doi:10.1016/j.ajog.2020.01.042 | Outcome
1255 | Yetti RE, Syafar M, Zulkifli A, The effect of family-based empowerment on obesity among adolescents in Tana Toraja. Article. Pakistan Journal of Nutrition. 2019;18(9):866–872. | Study design; Country
1256 | Yi SY, Steffen LM, Haring B, Rebholz CM, Mosley TH, Shah AM. Associations of the Dietary Approaches to Stop Hypertension dietary pattern with cardiac structure and function. Article. Nutr Metab Cardiovasc Dis. Nov 29 2021;31(12):3345–3351. doi: 10.1016/j.numecd.2021.08.050 34635365 | Outcome
1257 | Yi SY, Steffen LM, Zhou X, Shikany JM, Jacobs DR, Jr. Association of nut consumption with CVD risk factors in young to middle-aged adults: The Coronary Artery Risk Development in Young Adults (CARDIA) study. Nutr Metab Cardiovasc Dis. Oct 2022;32(10):2321–2329. doi: 10.1016/j.numecd.2022.07.013 35970686 | Intervention or Exposure
1258 | Yisahak SF, Hinkle SN, Mumford SL, Vegetarian diets during pregnancy, and maternal and neonatal outcomes. Int J Epidemiol. Mar 3 2021;50(1):165–178. doi:10.1093/ije/dyaa200 33232446 | Intervention or Exposure - Foods/Beverages Not Reported
1259 | Yisahak SF, Mumford SL, Grewal J, Maternal diet patterns during early pregnancy in relation to neonatal outcomes. Article. Am J Clin Nutr. Jul 1 2021;114(1):358–367. doi:10.1093/ajcn/nqab019 33742192 | Outcome
1260 | Yokose C, McCormick N, Lu N, Joshi AD, Curhan G, Choi HK. Adherence to 2020 to 2025 Dietary Guidelines for Americans and the Risk of New-Onset Female Gout. Article in Press. JAMA Intern Med. Mar 1 2022;182(3):254–264. doi:10.1001/jamainternmed.2021.7419 35099520 | Outcome
1262 | Yong HY, Mohd Shariff Z, Mohd Yusof BN, Pre-Pregnancy BMI Influences the Association of Dietary Quality and Gestational Weight Gain: The SECOST Study. Article. Int J Environ Res Public Health. Oct 4 2019;16(19)doi:10.3390/ijerph16193735 | Data overlap
1263 | Yoong SL, Grady A, Seward K, The Impact of a Childcare Food Service Intervention on Child Dietary Intake in Care: An Exploratory Cluster Randomized Controlled Trial. Journal Article; Randomized Controlled Trial; Research Support, Non-U.S. Gov't. Am J Health Promot. Sep 2019;33(7):991–1001. doi: 10.1177/0890117119837461 30909715 | Intervention or Exposure; Outcome
1264 | Yu D, Chen W, Zhang J, Effects of weight loss on bone turnover, inflammatory cytokines, and adipokines in Chinese overweight and obese adults. J Endocrinol Invest. Sep 2022;45(9):1757–1767. doi:10.1007/s40618-022-01815-5 35635643 | Intervention or Exposure
1265 | Yu EY, Ren Z, Mehrkanoon S, Plasma metabolomic profiling of dietary patterns associated with glucose metabolism status: The Maastricht Study. Article. BMC Med. Nov 21 2022;20(1):450. doi:10.1186/s12916-022-02653-1 36414942 | Outcome
1266 | Yu Y, Feng C, Bedard B, Fraser W, Dubois L. Diet quality during pregnancy and its association with social factors: 3D Cohort Study (Design, Develop, Discover). Matern Child Nutr. Oct 2022;18(4):e13403. doi: 10.1111/mcn.13403 35821643 | Outcome
1267 | Zaragoza-Marti A, Sanchez-SanSegundo M, Ferrer-Cascales R, Gabaldon-Bravo EM, Laguna-Perez A, Rumbo-Rodriguez L. Effects of the Mediterranean Lifestyle During the COVID-19 Lockdown in Spain: Preliminary Study. Front Nutr. 2021;8:683261. doi: 10.3389/fnut.2021.683261 34222306 | Intervention or Exposure; Comparator
1268 | Zarrinpar A. A high-protein diet prevents weight regain. Article. Nat Metab. Dec 2022;4(12):1616–1617. doi: 10.1038/s42255-022-00699-2 36456725 | Study design; Publication status; Non-human data
1269 | Zelicha H, Kloting N, Kaplan A, The effect of high-polyphenol Mediterranean diet on visceral adiposity: the DIRECT PLUS randomized controlled trial. BMC Med. Sep 30 2022;20(1):327. doi:10.1186/s12916-022-02525-8 36175997 | Comparator
1270 | Zenun Franco R, Fallaize R, Weech M, Hwang F, Lovegrove JA. Effectiveness of Web-Based Personalized Nutrition Advice for Adults Using the eNutri Web App: Evidence From the EatWellUK Randomized Controlled Trial. J Med Internet Res. Apr 25 2022;24(4):e29088. doi:10.2196/29088 35468093 | Duration of Intervention; Size or Power
1271 | Zhang B, Xu K, Mi B, Maternal Dietary Inflammatory Potential and Offspring Birth Outcomes in a Chinese Population. J Nutr. May 2023;153(5):1512–1523. doi:10.1016/j.tjnut.2023.03.006 37029046 | Study design; Intervention or Exposure - Foods/Beverages Not Reported
1272 | Zhang J, Hayden K, Jackson R, Schutte R. Association of red and processed meat consumption with cardiovascular morbidity and mortality in participants with and without obesity: A prospective cohort study. Clinical Nutrition. 2021;40(5):3643–3649.33413912 | Intervention or Exposure; Outcome
1273 | Zhang J, Wang H, Wang Z, Trajectories of Dietary Patterns and Their Associations with Overweight/Obesity among Chinese Adults: China Health and Nutrition Survey 1991–2018. Article. Nutrients. Aug 18 2021;13(8)doi:10.3390/nu13082835 | Country
1274 | Zhang J, Zhang Y, Huo S, Emotional Eating in Pregnant Women during the COVID-19 Pandemic and Its Association with Dietary Intake and Gestational Weight Gain. Nutrients. Jul 28 2020;12(8)doi:10.3390/nu12082250 | Intervention or Exposure
1275 | Zhang N, Zhou MZ, Li MX, Ma GS. Effects of Smartphone-Based Remote Interventions on Dietary Intake, Physical Activity, Weight Control, and Related Health Benefits Among the Older Population With Overweight and Obesity in China: Randomized Controlled Trial. Journal of Medical Internet Research. Apr 28 2023;25 doi:ARTN e41926.10.2196/41926 | Size or Power
1276 | Zhang S, Dukuzimana J, Stubbendorff A, Ericson U, Borne Y, Sonestedt E. Adherence to the EAT-Lancet diet and risk of coronary events in the Malmo Diet and Cancer cohort study. Am J Clin Nutr. May 2023;117(5):903–909. doi:10.1016/j.ajcnut.2023.02.018 36841443 | Outcome
1277 | Zhang X, Wang Y, Liu W, Diet quality, gut microbiota, and microRNAs associated with mild cognitive impairment in middle-aged and elderly Chinese population. Article. Am J Clin Nutr. Aug 2 2021;114(2):429–440. doi:10.1093/ajcn/nqab078 33871591 | Outcome; Country
1278 | Zhang X, Xiao D, Guzman G, Edirisinghe I, Burton-Freeman B. Avocado Consumption for 12 Weeks and Cardiometabolic Risk Factors: A Randomized Controlled Trial in Adults with Overweight or Obesity and Insulin Resistance. J Nutr. Aug 9 2022;152(8):1851–1861. doi:10.1093/jn/nxac126 35700149 | Intervention or Exposure - Foods/Beverages Not Reported; Comparator
1279 | Zhang Y, Wang YL, Zhang SW, Zhang YL, Zhang Q, Compli CNDC. Complex Association Among Diet Styles, Sleep Patterns, and Obesity in Patients with Diabetes. Diabet Metab Synd Ob. 2023;16:749–767. doi:10.2147/Dmso.S390101 | Health Status- 100% Diabetes
1280 | Zhang Y, Wei Y, Tang D, Association of major dietary patterns and different obesity phenotypes in Southwest China: the China Multi-Ethnic Cohort (CMEC) Study. Eur J Nutr. Feb 2023;62(1):465–476. doi:10.1007/s00394-022-02997-7 36089644 | Study design
1281 | Zhao L, Teong XT, Liu K, Eating architecture in adults at increased risk of type 2 diabetes: Associations with body fat and glycaemic control. Article in Press. British Journal of Nutrition. 2021; | Study design; Intervention or Exposure
1282 | Zhao L, Zhang P, Zheng Q, Deka A, Choudhury R, Rastogi S. Does a MediDiet With Additional Extra Virgin Olive Oil and Pistachios Reduce the Incidence of Gestational Diabetes? Article. Endocr Pract. Feb 2022;28(2):135–141. doi:10.1016/j.eprac.2021.08.010 34481972 | Outcome
1283 | Zheng M, Lioret S, Hesketh KD, Spence A, Taylor R, Campbell KJ. Association Between Longitudinal Trajectories of Lifestyle Pattern and BMI in Early Childhood. Obesity (Silver Spring). May 2021;29(5):879–887. doi:10.1002/oby.23136 33899335 | Intervention or Exposure
1284 | Zheng M, Yu HJ, He QQ, Protein Intake During Infancy and Subsequent Body Mass Index in Early Childhood: Results from the Melbourne InFANT Program. J Acad Nutr Diet. Sep 2021;121(9):1775–1784. doi:10.1016/j.jand.2021.02.022 33839065 | Intervention or Exposure
1285 | Zhou J, Leepromrath S, Tian X, Zhou D. Dynamics of Chinese Diet Divergence from Chinese Food Pagoda and Its Association with Adiposity and Influential Factors: 2004–2011. Int J Environ Res Public Health. Jan 13 2020; 17(2)doi:10.3390/ijerph17020507 | Study design
1286 | Zhou J, Leepromrath S, Zhou D. Dietary diversity indices v. dietary guideline-based indices and their associations with noncommunicable diseases, overweight and energy intake: evidence from China. Public Health Nutr. May 2023;26(5):911–933. doi:10.1017/S1368980022000556 35260208 | Country
1287 | Zhou L, Li H, Zhang S, Yang H, Ma Y, Wang Y. Impact of ultra-processed food intake on the risk of COVID-19: a prospective cohort study. Eur J Nutr. Feb 2023;62(1):275–287. doi:10.1007/s00394-022-02982-0 35972529 | Outcome
1288 | Zhu Q, Xue K, Guo HW, Yang YH. LMX1B rs10733682 Polymorphism Interacts with Macronutrients, Dietary Patterns on the Risk of Obesity in Han Chinese Girls. Nutrients. Apr 26 2020;12(5)doi:10.3390/nu12051227 | Study design; Comparator
1289 | Zhu R, Fogelholm M, Jalo E, Animal-based food choice and associations with long-term weight maintenance and metabolic health after a large and rapid weight loss: The PREVIEW study. Article. Clin Nutr. Apr 2022;41(4):817–828. doi:10.1016/j.clnu.2022.02.002 35263691 | Duration of Intervention
1290 | Zhu R, Fogelholm M, Poppitt SD, Adherence to a Plant-Based Diet and Consumption of Specific Plant Foods-Associations with 3-Year Weight-Loss Maintenance and Cardiometabolic Risk Factors: A Secondary Analysis of the PREVIEW Intervention Study. Article. Nutrients. Nov 1 2021;13(11)doi:10.3390/nu13113916 | Size or Power
1291 | Zhu S, Zhao A, Lan H, Nausea and Vomiting during Early Pregnancy among Chinese Women and Its Association with Nutritional Intakes. Nutrients. Feb 13 2023;15(4)doi:10.3390/nu15040933 | Study design; Intervention or Exposure
1292 | Zhu Y, Hedderson MM, Brown SD, Healthy preconception and early-pregnancy lifestyle and risk of preterm birth: a prospective cohort study. Am J Clin Nutr. Aug 2 2021;114(2):813–821. doi:10.1093/ajcn/nqab089 33900396 | Outcome
1293 | Zhu Y, Hedderson MM, Sridhar S, Xu F, Feng J, Ferrara A. Poor diet quality in pregnancy is associated with increased risk of excess fetal growth: A prospective multi-racial/ethnic cohort study. Article. International Journal of Epidemiology. 2019;48(2):423–432.30590563 | Data overlap
1294 | Zhu Y. Are you what you eat? Through the lens of prepregnancy plant-based diets and risk of gestational diabetes. Am J Clin Nutr. Dec 1 2021;114(6):1892–1893. doi:10.1093/ajcn/nqab334 34753178 | Study design; Publication status
1295 | Zinn C, McPhee J, Harris N, Williden M, Prendergast K, Schofield G. A 12-week low-carbohydrate, high-fat diet improves metabolic health outcomes over a control diet in a randomised controlled trial with overweight defence force personnel. Academic Journal. Appl Physiol Nutr Metab. Nov 2017;42(11):1158–1164. doi: 10.1139/apnm-2017-0260 28700832 | Intervention or Exposure - Foods/Beverages Not Reported
1296 | Zomeno MD, Lassale C, Perez-Vega A, Halo effect of a Mediterranean-lifestyle weight-loss intervention on untreated family members' weight and physical activity: a prospective study. Int J Obes (Lond). Jun 2021;45(6):1240–1248. doi: 10.1038/s41366-021-00763-z 33658686 | Intervention or Exposure; Outcome
1297 | Zoszak K, Neale E, Tapsell L, Probst Y. Exploring dietary changes in an interdisciplinary intervention trial: Application of a dietary guidelines food composition database. J Hum Nutr Diet. Apr 2021;34(2):265–272. doi: 10.1111/jhn.12790 32725838 | Intervention or Exposure; Outcome
1298 | Zuercher MD, Harvey DJ, Santiago-Torres M, Dietary inflammatory index and cardiovascular disease risk in Hispanic women from the Women's Health Initiative. Nutr J. Jan 12 2023;22(1):5. doi:10.1186/s12937-023-00838-9 36631866 | Study design; Outcome