# Appendix 2 Conclusion statements from the existing systematic review(s)

Table A 2 Conclusion statements from the existing systematic review(s) for the research question: What is the relationship between dietary patterns consumed and growth, body composition, and risk of obesity?

Citation | Conclusion statement and grade
Dietary Patterns Technical Expert Collaborative and NESR Staff. A Series of Systematic Reviews on the Relationship Between Dietary Patterns and Health Outcomes. March 2014. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/sites/default/files/2019-06/DietaryPatternsReport-FullFinal2.pdf | There is moderate evidence that in adults increased adherence to dietary patterns scoring high in fruits, vegetables, whole grains, legumes, unsaturated oils, and fish; low in total meat, saturated fat, cholesterol, sugar sweetened foods and drinks and sodium; and moderate in dairy products and alcohol is associated with more favorable outcomes related to body weight or risk of obesity, with some reports of variation based on gender, race, or body weight status. (Grade: II - Moderate) (Index Analysis); There is moderate evidence that adherence to a dietary pattern that emphasizes vegetables, fruits, and whole grains is associated with modest benefits in preventing weight gain or promoting weight loss in adults.(Grade: II - Moderate) (Other Methods); Limited and inconsistent evidence from epidemiological studies examining dietary patterns derived using factor or cluster analysis in adults found that consumption of a dietary pattern characterized by vegetables, fruits, whole grains, and reduced-fat dairy products tends to be associated with more favorable body weight status over time than consumption of a dietary pattern characterized by red meat, processed meats, sugar-sweetened foods and drinks, and refined grains. (Grade: III - Limited) (Factor or Cluster Analysis); There are a number of methodological differences among the studies examining the relationship between dietary patterns derived using reduced rank regression and body weight status. The disparate nature of these studies made it difficult to compare results, and therefore, no conclusions were drawn. (Grade: IV - Not Assignable) (Reduced Rank Regression)
English LK, Obbagy JE, Wong YP, Psota TL, Nadaud P, Johns K, Terry N, Butte NF, Dewey KG, Fleischer DM, Fox MK, Greer FR, Krebs NF, Scanlon KS, Casavale KO, Spahn JM, Stoody E. Types and Amounts of Complementary Foods and Beverages and Growth, Size, and Body Composition: A Systematic Review. April 2019. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.PB242018.SR0306 | No conclusion could be made about the relationship between distinct dietary patterns during the complementary feeding period and growth, size, body composition, and/or prevalence/incidence of malnutrition, overweight or obesity. (Grade: Grade Not Assignable)
Boushey C, Ard J, Bazzano L, Heymsfield S, Mayer-Davis E, Sabaté J, Snetselaar L, Van Horn L, Schneeman B, English LK, Bates M, Callahan E, Butera G, Terry N, Obbagy J. Dietary Patterns and Growth, Size, Body Composition, and/or Risk of Overweight or Obesity: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0101 | The 2020 Dietary Guidelines Advisory Committee reviewed newly published evidence using a systematic evidence scan and determined that the conclusion drawn by the 2015 Dietary Guidelines Advisory Committee generally reflects the current state of science. Moderate evidence indicates dietary patterns emphasizing vegetables, fruits, and whole grains; seafood and legumes; moderate in dairy products (particularly low and non-fat dairy) and alcohol; lower in meats (including red and processed meats), and low in sugar-sweetened foods and beverages, and refined grains are associated with favorable outcomes related to body weight, (including lower BMI, waist circumference, or percent body fat) or risk of obesity. Components of the dietary patterns associated with these favorable outcomes include higher intakes of unsaturated fats and lower intakes of saturated fats, cholesterol, and sodium. (2015 Dietary Guidelines Advisory Committee Grade: Moderate); Limited evidence suggests that dietary patterns consumed by children or adolescents that are lower in fruits, vegetables, whole grains, and low-fat dairy while being higher in added sugars, refined grains, fried potatoes, and processed meats are associated with higher fat-mass index and BMI later in adolescence. (Grade: Limited); No evidence is available to determine a relationship between diets based on macronutrient distribution consumed during childhood and growth, size, body composition, and risk of overweight/obesity. (Grade: Grade not assignable); No conclusion could be made about the relationship between distinct dietary patterns during the complementary feeding period and growth, size, body composition, and/or prevalence/incidence of malnutrition, overweight or obesity. (Grade: Grade Not Assignable)
Donovan S, Dewey K, Novotny R, Stang J, Taveras E, Kleinman R, Raghavan R, Nevins J, Scinto-Madonich S, Kim JH, Terry N, Butera G, Obbagy J. Dietary Patterns during Pregnancy and Gestational Weight Gain: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0201 | Limited evidence suggests that certain dietary patterns during pregnancy are associated with a lower risk of excessive gestational weight gain during pregnancy. These patterns are higher in vegetables, fruits, nuts, legumes, fish, and lower in added sugar, and red and processed meat. (Grade: Limited)
Donovan S, Dewey K, Novotny R, Stang J, Taveras E, Kleinman R, Raghavan R, Nevins J, Scinto-Madonich S, Kim JH, Terry N, Butera G, Obbagy J. Dietary Patterns during Lactation and Postpartum Weight Loss: A Systematic Review. July 2020. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: 10.52570/NESR.DGAC2020.SR0202 | Insufficient evidence is available to determine the relationship between dietary patterns during lactation and postpartum weight loss. (Grade: Grade not assignable)