# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
BMI: Body mass index
GWG: Gestational weight gain
GWGR: Gestational weight gain rate
HDI: Human Development Index
HHS: United States Department of Health and Human Services
HMF: Human milk feeding
NESR: Nutrition Evidence Systematic Review
PPWC: Postpartum weight change
PPWR: Postpartum weight retention
RCT: Randomized controlled trial
SEP: Socioeconomic position
USDA: United States Department of Agriculture
UPF: Ultra-processed food