# References of the articles included in the systematic review

1 Abbott L, Gordon Schluck G, Graven L, Martorella G. Exploring the intervention effect moderators of a cardiovascular health promotion study among rural African-Americans. Public Health Nurs. Mar 2018;35(2):126–134. doi:10.1111/phn.12377. Epub 2017 Nov 28.29193414
2 Abbott L, Williams C, Slate E, Gropper S. Promoting Heart Health Among Rural African Americans. J Cardiovasc Nurs. Jan/Feb 2018;33(1):E8–e14. doi:10.1097/JCN.0000000000000410.28353542
3 Abbott LS, Slate EH, Lemacks JL. Influencing cardiovascular health habits in the rural, deep south: results of a cluster randomized trial. Health Educ Res. Apr 1 2019;34(2):200–208. doi:10.1093/her/cyy052.30601979
4 Abbott LS, Slate EH, Graven LJ. Cardiovascular disease risk among rural residents living with diabetes and prediabetes: A cluster randomized trial. Public Health Nurs. Jan 2020;37(1):16–24. doi:10.1111/phn.12659. Epub 2019 Sep 5.31489717
5 Amaro H, Cortés DE, Garcia S, Duan L, Black DS. Video-Based Grocery Shopping Intervention Effect on Purchasing Behaviors Among Latina Shoppers. Am J Public Health. May 2017;107(5):800–806. doi:10.2105/AJPH.2017.303725. Epub 2017 Mar 21.28323473
6 Anand SS, Davis AD, Ahmed R, A family-based intervention to promote healthy lifestyles in an aboriginal community in Canada. Can J Public Health. Nov-Dec 2007;98(6):447–52. doi:10.1007/BF03405436.19039880
7 Ard JD, Rosati R, Oddone EZ. Culturally-sensitive weight loss program produces significant reduction in weight, blood pressure, and cholesterol in eight weeks. J Natl Med Assoc. Nov 2000;92(11):515–23.11152083
8 Ard JD, Cox TL, Zunker C, Wingo BC, Jefferson WK, Brakhage C. A study of a culturally enhanced EatRight dietary intervention in a predominately African American workplace. J Public Health Manag Pract. Nov-Dec 2010;16(6):E1–8. doi:10.1097/PHH.0b013e3181ce5538.
9 Ard JD, Carson TL, Shikany JM, Weight loss and improved metabolic outcomes amongst rural African American women in the Deep South: six-month outcomes from a community-based randomized trial. J Intern Med. Jul 2017;282(1):102–113. doi:10.1111/joim.12622. Epub 2017 May 17.28514081
10 Arlinghaus KR, Moreno JP, Reesor L, Hernandez DC, Johnston CA. Compañeros: High School Students Mentor Middle School Students to Address Obesity Among Hispanic Adolescents. Prev Chronic Dis. Oct 12 2017;14:E92. doi:10.5888/pcd14.170130.29023233
11 Arredondo EM, Ayala GX, Soto S, Latina mothers as agents of change in children's eating habits: findings from the randomized controlled trial Entre Familia: Reflejos de Salud. Int J Behav Nutr Phys Act. Oct 1 2018;15(1):95. doi:10.1186/s12966-018-0714-0.30285755
12 Auslander W, Haire-Joshu D, Houston C, Rhee CW, Williams JH. A controlled evaluation of staging dietary patterns to reduce the risk of diabetes in African-American women. Diabetes Care. May 2002;25(5):809–14. doi:10.2337/diacare.25.5.809.11978673
13 Aycock DM, Clark PC, Hayat MJ, Salazar LF, Eriksen MP. Stroke Counseling Intervention for Young Adult African Americans: A Randomized Controlled Trial. Nurs Res. Mar-Apr 01 2023;72(2):83–92. doi:10.1097/NNR.0000000000000633. Epub 2022 Dec 9.36729696
14 Babatunde OA, Arp Adams S, Truman S, The impact of a randomized dietary and physical activity intervention on chronic inflammation among obese African-American women. Women Health. Aug 2020;60(7):792–805. doi:10.1080/03630242.2020.1746950. Epub 2020 Apr 5.32248760
15 Backman D, Scruggs V, Atiedu AA, Using a Toolbox of tailored educational lessons to improve fruit, vegetable, and physical activity behaviors among African American women in California. J Nutr Educ Behav. Jul-Aug 2011;43(4 Suppl 2):S75–85. doi:10.1016/j.jneb.2011.02.004.21683294
16 Bains A, Pakseresht M, Roache C, Healthy Foods North improves diet among Inuit and Inuvialuit women of childbearing age in Arctic Canada. J Hum Nutr Diet. Apr 2014;27 Suppl 2:175–85. doi:10.1111/jhn.12134. Epub 2013 Jun 28.23808787
17 Balcázar HG, e Heer H, Rosenthal L, A promotores de salud intervention to reduce cardiovascular disease risk in a high-risk Hispanic border population, 2005–2008. Prev Chronic Dis. Mar 2010;7(2):A28.20158973
18 Baltaci A, Hurtado Choque GA, Davey C, Padres Preparados, Jóvenes Saludables: intervention impact of a randomized controlled trial on Latino father and adolescent energy balance-related behaviors. BMC Public Health. Oct 18 2022;22(1):1932. doi:10.1186/s12889-022-14284-5.36258168
19 Barkin SL, Gesell SB, Po'e EK, Escarfuller J, Tempesti T. Culturally tailored, family-centered, behavioral obesity intervention for Latino-American preschool-aged children. Pediatrics. Sep 2012;130(3):445–56. doi:10.1542/peds.2011-3762. Epub 2012 Aug 6.22869834
20 Barnidge EK, Baker EA, Schootman M, Motton F, Sawicki M, Rose F. The effect of education plus access on perceived fruit and vegetable consumption in a rural African American community intervention. Health Educ Res. Oct 2015;30(5):773–85. doi:10.1093/her/cyv041. Epub 2015 Sep 2.26338985
21 Barragan M, Luna V, Hammons AJ, Reducing Obesogenic Eating Behaviors in Hispanic Children through a Family-Based, Culturally-Tailored RCT: Abriendo Caminos. Int J Environ Res Public Health. Feb 9 2022;19(4)doi:10.3390/ijerph19041917.
22 Bean MK, Wilson DB, Thornton LM, Kelly N, Mazzeo SE. Dietary intake in a randomized-controlled pilot of NOURISH: a parent intervention for overweight children. Prev Med. Sep 2012;55(3):224–7. doi:10.1016/j.ypmed.2012.06.016. Epub 2012 Jun 24.22735041
23 Beech BM, Klesges RC, Kumanyika SK, Child- and parent-targeted interventions: the Memphis GEMS pilot study. Ethn Dis. Winter 2003;13(1 Suppl 1):S40–53.
24 Befort CA, Nollen N, Ellerbeck EF, Sullivan DK, Thomas JL, Ahluwalia JS. Motivational interviewing fails to improve outcomes of a behavioral weight loss program for obese African American women: a pilot randomized trial. J Behav Med. Oct 2008;31(5):367–77. doi:10.1007/s10865-008-9161-8. Epub 2008 Jun 28.18587639
25 Bender MS, Cooper BA, Flowers E, Ma R, Arai S. Filipinos Fit and Trim - A feasible and efficacious DPP-based intervention trial. Contemp Clin Trials Commun. Dec 2018;12:76–84. doi:10.1016/j.conctc.2018.09.004. eCollection 2018 Dec.30294699
26 Beresford SAA, Ornelas IJ, Bauer MC, Group Randomized Trial of Healthy Eating and Gardening Intervention in Navajo Elementary Schools (Yéego!). AJPM Focus. Dec 2022;1(2):100033. doi:10.1016/j.focus.2022.100033. eCollection 2022 Dec.37791240
27 Bernhart JA, Turner-McGrievy GM, Wilson MJ, Sentman C, Wilcox S, Rudisill C. NEW Soul in the neighborhood-reach and effectiveness of a dissemination and implementation feasibility study. Transl Behav Med. Apr 3 2023;13(3):123–131. doi:10.1093/tbm/ibac080.36689305
28 Berry D, Verbiest S, Hall EG, A Postpartum Community-Based Weight Management Intervention Designed for Low-Income Women: Feasibility and Initial Efficacy Testing. J Natl Black Nurses Assoc. Jul 2015;26(1):29–39.26371358
29 Bersamin A, Izumi BT, Nu J, O'Brien D M, Paschall M. Strengthening adolescents' connection to their traditional food system improves diet quality in remote Alaska Native communities: results from the Neqa Elicarvigmun Pilot Study. Transl Behav Med. Oct 1 2019;9(5):952–961. doi:10.1093/tbm/ibz087.31570921
30 Black MM, Hager ER, Le K, Challenge! Health promotion/obesity prevention mentorship model among urban, black adolescents. Pediatrics. Aug 2010;126(2):280–8. doi:10.1542/peds.2009-1832. Epub 2010 Jul 26.20660556
31 Blow J, Sagaribay R, rd C. A pilot study examining the impact of a brief health education intervention on food choices and exercise in a Latinx college student sample. Appetite. Jun 1 2022;173:105979. doi:10.1016/j.appet.2022.105979. Epub 2022 Mar 1.35245642
32 Bopp M, Wilcox S, Laken M, 8 Steps to Fitness: a faith-based, behavior change physical activity intervention for African Americans. J Phys Act Health. Sep 2009;6(5):568–77. doi:10.1123/jpah.6.5.568.19953833
33 Brewer LC, Jenkins S, Hayes SN, Community-Based, Cluster-Randomized Pilot Trial of a Cardiovascular Mobile Health Intervention: Preliminary Findings of the FAITH! Trial. Circulation. Jul 19 2022;146(3):175–190. doi:10.1161/CIRCULATIONAHA.122.059046. Epub 2022 Jul 18.35861762
34 Brown B, Noonan C, Harris KJ, Developing and piloting the Journey to Native Youth Health program in Northern Plains Indian communities. Diabetes Educ. Jan-Feb 2013;39(1):109–18. doi:10.1177/0145721712465343. Epub 2012 Nov 13.23150531
35 Brown DL, Conley KM, Sánchez BN, A Multicomponent Behavioral Intervention to Reduce Stroke Risk Factor Behaviors: The Stroke Health and Risk Education Cluster-Randomized Controlled Trial. Stroke. Oct 2015;46(10):2861–7. doi:10.1161/STROKEAHA.115.010678. Epub 2015 Sep 15.26374480
36 Brown B, Dybdal L, Noonan C, Pedersen MG, Parker M, Corcoran M. Group Gardening in a Native American Community: A Collaborative Approach. Health Promot Pract. Jul 2020;21(4):611–623. doi:10.1177/1524839919830930. Epub 2019 Feb 20.30786795
37 Buller DB, Woodall WG, Zimmerman DE, Randomized trial on the 5 a day, the Rio Grande Way Website, a web-based program to improve fruit and vegetable consumption in rural communities. J Health Commun. Apr-May 2008;13(3):230–49. doi:10.1080/10810730801985285.18569356
38 Caballero B, Clay T, Davis SM, Pathways: a school-based, randomized controlled trial for the prevention of obesity in American Indian schoolchildren. Am J Clin Nutr. Nov 2003;78(5):1030–8. doi:10.1093/ajcn/78.5.1030.14594792
39 Cepni AB, Taylor A, Crumbley C, Feasibility and Efficacy of the "FUNPALs Playgroup" Intervention to Improve Toddler Dietary and Activity Behaviors: A Pilot Randomized Controlled Trial. Int J Environ Res Public Health. Jul 23 2021;18(15)doi:10.3390/ijerph18157828.
40 Chen JL, Weiss S, Heyman MB, Lustig RH. Efficacy of a child-centred and family-based program in promoting healthy weight and healthy behaviors in Chinese American children: a randomized controlled study. J Public Health (Oxf). Jun 2010;32(2):219–29. doi:10.1093/pubmed/fdp105. Epub 2009 Nov 15.19933120
41 Chen Q, Goto K, Wolff C, Bianco-Simeral S, Gruneisen K, Gray K. Cooking up diversity. Impact of a multicomponent, multicultural, experiential intervention on food and cooking behaviors among elementary-school students from low-income ethnically diverse families. Appetite. Sep 2014;80:114–22. doi:10.1016/j.appet.2014.05.009. Epub 2014 May 15.24845782
42 Chen JL, Guedes CM, Lung AE. Smartphone-based Healthy Weight Management Intervention for Chinese American Adolescents: Short-term Efficacy and Factors Associated With Decreased Weight. J Adolesc Health. Apr 2019;64(4):443–449. doi:10.1016/j.jadohealth.2018.08.022. Epub 2018 Nov 6.30409751
43 Christian JG, Byers TE, Christian KK, A computer support program that helps clinicians provide patients with metabolic syndrome tailored counseling to promote weight loss. J Am Diet Assoc. Jan 2011;111(1):75–83. doi:10.1016/j.jada.2010.10.006.21185968
44 Clarke P, Evans SH, Hovy EH. Indigenous message tailoring increases consumption of fresh vegetables by clients of community pantries. Health Commun. Sep 2011;26(6):571–82. doi:10.1080/10410236.2011.558337. Epub 2011 Jun 24.21512926
45 Cloutier MM, Wiley JF, Kuo CL, Cornelius T, Wang Z, Gorin AA. Outcomes of an early childhood obesity prevention program in a low-income community: a pilot, randomized trial. Pediatr Obes. Nov 2018;13(11):677–685. doi:10.1111/ijpo.12458. Epub 2018 Aug 28.30156058
46 Cousins JH, Rubovits DS, Dunn JK, Reeves RS, Ramirez AG, Foreyt JP. Family versus individually oriented intervention for weight loss in Mexican American women. Public health reports (Washington, DC: 1974). 1992 1992;107(5):549–55.
47 Crespo NC, Elder JP, Ayala GX, Results of a multi-level intervention to prevent and control childhood obesity among Latino children: the Aventuras Para Niños Study. Ann Behav Med. Feb 2012;43(1):84–100. doi:10.1007/s12160-011-9332-7.22215470
48 Davis JN, Ventura EE, Alexander KE, Feasibility of a home-based versus classroom-based nutrition intervention to reduce obesity and type 2 diabetes in Latino youth. Int J Pediatr Obes. 2007;2(1):22–30. doi:10.1080/17477160601133077.17763007
49 Davis JN, Kelly LA, Lane CJ, Randomized control trial to improve adiposity and insulin resistance in overweight Latino adolescents. Obesity (Silver Spring). Aug 2009;17(8):1542–8. doi:10.1038/oby.2009.19. Epub 2009 Feb 26.19247280
50 Davis JN, Ventura EE, Cook LT, Gyllenhammer LE, Gatto NM. LA Sprouts: a gardening, nutrition, and cooking intervention for Latino youth improves diet and reduces obesity. J Am Diet Assoc. Aug 2011;111(8):1224–30. doi:10.1016/j.jada.2011.05.009.21802571
51 Davis SM, Myers OB, Cruz TH, CHILE: Outcomes of a group randomized controlled trial of an intervention to prevent obesity in preschool Hispanic and American Indian children. Prev Med. Aug 2016;89:162–168. doi:10.1016/j.ypmed.2016.05.018. Epub 2016 May 21.27222162
52 de Heer HD, Koehly L, Pederson R, Morera O. Effectiveness and spillover of an after-school health promotion program for Hispanic elementary school children. Am J Public Health. Oct 2011;101(10):1907–13. doi:10.2105/AJPH.2011.300177. Epub 2011 Aug 18.21852659
53 Derose KP, Williams MV, Flórez KR, Eat, Pray, Move: A Pilot Cluster Randomized Controlled Trial of a Multilevel Church-Based Intervention to Address Obesity Among African Americans and Latinos. Am J Health Promot. May 2019;33(4):586–596. doi:10.1177/0890117118813333. Epub 2018 Nov 25.30474376
54 Di Noia J, Monica D, Sikorskii A. Process Evaluation of a Farm-to-WIC Intervention. J Acad Nutr Diet. Oct 2021;121(10):2021–2034. doi:10.1016/j.jand.2021.05.014. Epub 2021 Jun 16.34144918
55 Duggan C, Carosso E, Mariscal N, Diabetes prevention in Hispanics: report from a randomized controlled trial. Prev Chronic Dis. Feb 27 2014;11:E28. doi:10.5888/pcd11.130119.24576395
56 Falbe J, Cadiz AA, Tantoco NK, Thompson HR, Madsen KA. Active and Healthy Families: A Randomized Controlled Trial of a Culturally Tailored Obesity Intervention for Latino Children. Acad Pediatr. Jul-Aug 2015;15(4):386–95. doi:10.1016/j.acap.2015.02.004. Epub 2015 Apr 28.25937516
57 Fardy PS, White RE, Clark LT, Health promotion in minority adolescents: a Healthy People 2000 pilot study. Journal of cardiopulmonary rehabilitation. 1995 1995;15(1):65–72.8529088
58 Faridi Z, Shuval K, Njike VY, Partners reducing effects of diabetes (PREDICT): a diabetes prevention physical activity and dietary intervention through African-American churches. Health Educ Res. Apr 2010;25(2):306–15. doi:10.1093/her/cyp005. Epub 2009 Mar 4.19261690
59 Fitzgibbon ML, Stolley MR, Ganschow P, Results of a faith-based weight loss intervention for black women. J Natl Med Assoc. Oct 2005;97(10):1393–402.16355489
60 Fitzgibbon ML, Stolley MR, Schiffer L, Van Horn L, KauferChristoffel K, Dyer A. Hip-Hop to Health Jr. for Latino preschool children. Obesity (Silver Spring). Sep 2006;14(9):1616–25.17030973
61 Flores R. Dance for health: improving fitness in African American and Hispanic adolescents. Public health reports (Washington, DC: 1974). 1995 1995;110(2):189–93.
62 Franckle RL, Levy DE, Macias-Navarro L, Rimm EB, Thorndike AN. Traffic-light labels and financial incentives to reduce sugar-sweetened beverage purchases by low-income Latino families: a randomized controlled trial. Public Health Nutr. Jun 2018;21(8):1426–1434. doi:10.1017/S1368980018000319. Epub 2018 Mar 1.29493476
63 Frerichs L, Bess K, Young TL, A Cluster Randomized Trial of a Community-Based Intervention Among African-American Adults: Effects on Dietary and Physical Activity Outcomes. Prev Sci. Apr 2020;21(3):344–354. doi:10.1007/s11121-019-01067-5.31925605
64 Gans KM, Risica PM, Strolla LO, Effectiveness of different methods for delivering tailored nutrition education to low income, ethnically diverse adults. Int J Behav Nutr Phys Act. May 5 2009;6:24. doi:10.1186/1479-5868-6-24.19416525
65 Gans KM, Risica PM, Keita AD, Multilevel approaches to increase fruit and vegetable intake in low-income housing communities: final results of the Ľive Well, Viva Bien' cluster-randomized trial. Int J Behav Nutr Phys Act. Aug 20 2018;15(1):80. doi:10.1186/s12966-018-0704-2.30126463
66 Garcia DO, Valdez LA, Aceves B, A Gender- and Culturally Sensitive Weight Loss Intervention for Hispanic Men: Results From the Animo Pilot Randomized Controlled Trial. Health Educ Behav. Oct 2019;46(5):763–772. doi:10.1177/1090198119853011. Epub 2019 Jun 19.31216875
67 Gaston MH, Porter GK, Thomas VG. Prime Time Sister Circles: evaluating a gender-specific, culturally relevant health intervention to decrease major risk factors in mid-life African-American women. J Natl Med Assoc. Apr 2007;99(4):428–38.17444433
68 Gatto NM, Ventura EE, Cook LT, Gyllenhammer LE, Davis JN. LA Sprouts: a garden-based nutrition intervention pilot program influences motivation and preferences for fruits and vegetables in Latino youth. J Acad Nutr Diet. Jun 2012;112(6):913–20. doi:10.1016/j.jand.2012.01.014. Epub 2012 Apr 18.22516551
69 Gittelsohn J, Vijayadeva V, Davison N, A food store intervention trial improves caregiver psychosocial factors and children's dietary intake in Hawaii. Obesity (Silver Spring). Feb 2010;18 Suppl 1:S84–90. doi:10.1038/oby.2009.436.
70 Gittelsohn J, Kim EM, He S, Pardilla M. A food store-based environmental intervention is associated with reduced BMI and improved psychosocial factors and food-related behaviors on the Navajo nation. J Nutr. Sep 2013;143(9):1494–500. doi:10.3945/jn.112.165266. Epub 2013 Jul 17.23864511
71 Halbert CH, Bellamy S, Briggs V, A comparative effectiveness education trial for lifestyle health behavior change in African Americans. Health Educ Res. Jun 1 2017;32(3):207–218. doi:10.1093/her/cyx039.28335038
72 Hammons AJ, Hannon BA, Teran-Garcia M, Effects of Culturally Tailored Nutrition Education on Dietary Quality of Hispanic Mothers: A Randomized Control Trial. J Nutr Educ Behav. Nov-Dec 2019;51(10):1168–1176. doi:10.1016/j.jneb.2019.06.017. Epub 2019 Jul 31.31375361
73 Harmon BE, Adams SA, Scott D, Gladman YS, Ezell B, Hebert JR. Dash of faith: a faith-based participatory research pilot study. J Relig Health. Jun 2014;53(3):747–59. doi:10.1007/s10943-012-9664-z.23224838
74 Hawkins M, Hosker M, Marcus BH, A pregnancy lifestyle intervention to prevent gestational diabetes risk factors in overweight Hispanic women: a feasibility randomized controlled trial. Diabet Med. Jan 2015;32(1):108–15. doi:10.1111/dme.12601. Epub 2014 Oct 29.25306925
75 Hayashi T, Farrell MA, Chaput LA, Rocha DA, Hernandez M. Lifestyle intervention, behavioral changes, and improvement in cardiovascular risk profiles in the California WISEWOMAN project. J Womens Health (Larchmt). Jun 2010;19(6):1129–38. doi:10.1089/jwh.2009.1631.20509780
76 Hébert JR, Wirth M, Davis L, C-reactive protein levels in African Americans: a diet and lifestyle randomized community trial. Am J Prev Med. Oct 2013;45(4):430–40. doi:10.1016/j.amepre.2013.05.011.24050419
77 Heredia NI, Lee M, Mitchell-Bennett L, Reininger BM. Tu Salud ¡Sí Cuenta! Your Health Matters! A Community-wide Campaign in a Hispanic Border Community in Texas. J Nutr Educ Behav. Nov-Dec 2017;49(10):801–809.e1. doi:10.1016/j.jneb.2017.06.008. Epub 2017 Aug 14.28818489
78 Herring SJ, Bersani VM, Santoro C, McNeil SJ, Kilby LM, Bailer B. Feasibility of using a peer coach to deliver a behavioral intervention for promoting postpartum weight loss in Black and Latina mothers. Transl Behav Med. Jun 17 2021;11(6):1226–1234. doi:10.1093/tbm/ibaa096.33184667
79 Horton LA, Parada H, Slymen DJ, Arredondo E, Ibarra L, Ayala GX. Targeting children's dietary behaviors in a family intervention: 'Entre familia: reflejos de salud'. Salud Publica Mex. 2013;55 Suppl 3:397–405.
80 Horton LA, Ayala GX, Slymen DJ, A Mediation Analysis of Mothers' Dietary Intake: The Entre Familia: Reflejos de Salud Randomized Controlled Trial. Health Educ Behav. Aug 2018;45(4):501–510. doi:10.1177/1090198117742439. Epub 2017 Dec 6.29212358
81 Islam NS, Zanowiak JM, Wyatt LC, A randomized-controlled, pilot intervention on diabetes prevention and healthy lifestyles in the New York City Korean community. J Community Health. Dec 2013;38(6):1030–41. doi:10.1007/s10900-013-9711-z.23813322
82 Islam NS, Zanowiak JM, Wyatt LC, Diabetes prevention in the New York City Sikh Asian Indian community: a pilot study. Int J Environ Res Public Health. May 19 2014;11(5):5462–86. doi:10.3390/ijerph110505462.24852392
83 Bird Jernigan VB, Salvatore AL, Williams M, A Healthy Retail Intervention in Native American Convenience Stores: The THRIVE Community-Based Participatory Research Study. Am J Public Health. Jan 2019;109(1):132–139. doi:10.2105/AJPH.2018.304749. Epub 2018 Nov 29.30495999
84 Johnson LT, Ralston PA, Jones E. Beauty salon health intervention increases fruit and vegetable consumption in African-American women. J Am Diet Assoc. Jun 2010;110(6):941–5. doi:10.1016/j.jada.2010.03.012.20497787
85 Kanaya AM, Santoyo-Olsson J, Gregorich S, Grossman M, Moore T, Stewart AL. The Live Well, Be Well study: a community-based, translational lifestyle program to lower diabetes risk factors in ethnic minority and lower-socioeconomic status adults. Am J Public Health. Aug 2012;102(8):1551–8. doi:10.2105/AJPH.2011.300456. Epub 2012 Jun 14.22698027
86 Kandula NR, Dave S, De Chavez PJ, Translating a heart disease lifestyle intervention into the community: the South Asian Heart Lifestyle Intervention (SAHELI) study; a randomized control trial. BMC Public Health. Oct 16 2015;15:1064. doi:10.1186/s12889-015-2401-2.26475629
87 Karanja N, Lutz T, Ritenbaugh C, The TOTS community intervention to prevent overweight in American Indian toddlers beginning at birth: a feasibility and efficacy study. J Community Health. Dec 2010;35(6):667–75. doi:10.1007/s10900-010-9270-5.20508978
88 Kerr JC, Valois RF, Farber NB, Effects of Promoting Health Among Teens on Dietary, Physical Activity and Substance Use Knowledge and Behaviors for African American Adolescents. Am J Health Educ. Jan 1 2013;44(4):191–202. doi:10.1080/19325037.2013.798218.23957017
89 Keyserling TC, Samuel-Hodge CD, Pitts SJ, A community-based lifestyle and weight loss intervention promoting a Mediterranean-style diet pattern evaluated in the stroke belt of North Carolina: the Heart Healthy Lenoir Project. BMC Public Health. Aug 5 2016;16:732. doi:10.1186/s12889-016-3370-9.27495295
90 Kieffer EC, Welmerink DB, Sinco BR, Dietary outcomes in a Spanish-language randomized controlled diabetes prevention trial with pregnant Latinas. Am J Public Health. Mar 2014;104(3):526–33. doi:10.2105/AJPH.2012.301122. Epub 2013 Jun 13.23763411
91 Kim KH, Linnan L, Campbell MK, Brooks C, Koenig HG, Wiesen C. The WORD (wholeness, oneness, righteousness, deliverance): a faith-based weight-loss program utilizing a community-based participatory research approach. Health Educ Behav. Oct 2008;35(5):634–50. doi:10.1177/1090198106291985. Epub 2006 Dec 15.17200103
92 Klesges RC, Obarzanek E, Kumanyika S, The Memphis Girls' health Enrichment Multi-site Studies (GEMS): an evaluation of the efficacy of a 2-year obesity prevention program in African American girls. Arch Pediatr Adolesc Med. Nov 2010;164(11):1007–14. doi:10.1001/archpediatrics.2010.196.21041593
93 Kolahdooz F, Pakseresht M, Mead E, Beck L, Corriveau A, Sharma S. Impact of the Healthy Foods North nutrition intervention program on Inuit and Inuvialuit food consumption and preparation methods in Canadian Arctic communities. Nutr J. Jul 4 2014;13:68. doi:10.1186/1475-2891-13-68.24993180
94 Koniak-Griffin D, Brecht ML, Takayanagi S, Villegas J, Melendrez M, Balcázar H. A community health worker-led lifestyle behavior intervention for Latina (Hispanic) women: feasibility and outcomes of a randomized controlled trial. Int J Nurs Stud. Jan 2015;52(1):75–87. doi:10.1016/j.ijnurstu.2014.09.005. Epub 2014 Sep 22.25307195
95 Kreuter MW, Sugg-Skinner C, Holt CL, Cultural tailoring for mammography and fruit and vegetable intake among low-income African-American women in urban public health centers. Prev Med. Jul 2005;41(1):53–62.15916993
96 Kumanyika SK, Shults J, Fassbender J, Outpatient weight management in African-Americans: the Healthy Eating and Lifestyle Program (HELP) study. Prev Med. Aug 2005;41(2):488–502. doi:10.1016/j.ypmed.2004.09.049.15917045
97 Kumanyika SK, Wadden TA, Shults J, Trial of family and friend support for weight loss in African American adults. Arch Intern Med. Oct 26 2009;169(19):1795–804. doi:10.1001/archinternmed.2009.337.19858438
98 Kwon SC, Wyatt LC, Kum SS, Evaluation of a Diabetes Prevention Intervention for Korean American immigrants at Risk for Diabetes. Health Equity. 2022;6(1):167–177. doi:10.1089/heq.2021.0137. eCollection 2022.35402771
99 Landry AS, Thomson JL, Huye HF, Yadrick K, Connell CL. Mississippi Communities for Healthy Living. Health Educ Behav. Apr 2017;44(2):316–325. doi:10.1177/1090198116657807. Epub 2016 Jul 18.27413029
100 Laviolette C, Johnson CM, Butler JL, Biediger-Friedman L, Sharkey JR. Nutrition Effects of a Family-Centered Health Promotion Program for Mexican-Heritage Children in the Lower Rio Grande Valley of Texas. Nutrients. Mar 25 2023;15(7)doi:10.3390/nu15071600.
101 Lesley ML. Social problem solving training for African Americans: effects on dietary problem solving skill and DASH diet-related behavior change. Patient Educ Couns. Jan 2007;65(1):137–46. doi:10.1016/j.pec.2006.07.001. Epub 2006 Sep 6.16950591
102 Lim S, Wyatt LC, Chauhan H, A Culturally Adapted Diabetes Prevention Intervention in the New York City Sikh Asian Indian Community Leads to Improvements in Health Behaviors and Outcomes. Health Behav Res. 2019;2(1)doi:10.4148/2572-1836.1027.
103 Mamun A, Kitzman H, Dodgen L. Reducing metabolic syndrome through a community-based lifestyle intervention in African American women. Nutr Metab Cardiovasc Dis. Sep 24 2020;30(10):1785–1794. doi:10.1016/j.numecd.2020.06.005. Epub 2020 Jun 12.32605881
104 Matias SL, Riden HE, Lee DS, Bang H, Schenker MB. Effectiveness of a worksite lifestyle intervention to reduce BMI among farmworkers in California: a cluster randomised controlled trial. Public Health Nutr. Sep 2022;25(9):2651–2659. doi:10.1017/S136898002200129X. Epub 2022 May 27.35620920
105 Mau MK, Glanz K, Severino R, Grove JS, Johnson B, Curb JD. Mediators of lifestyle behavior change in Native Hawaiians: initial findings from the Native Hawaiian Diabetes Intervention Program. Diabetes Care. Oct 2001;24(10):1770–5.11574440
106 Mayer VL, Vangeepuram N, Fei K, Outcomes of a Weight Loss Intervention to Prevent Diabetes Among Low-Income Residents of East Harlem, New York. Health Educ Behav. Dec 2019;46(6):1073–1082. doi:10.1177/1090198119868232. Epub 2019 Aug 23.31441328
107 McCarthy WJ, Yancey AK, Harrison GG, Leslie J, Siegel JM. Fighting cancer with fitness: dietary outcomes of a randomized, controlled lifestyle change intervention in healthy African-American women. Prev Med. Mar 2007;44(3):246–53. doi:10.1016/j.ypmed.2006.08.019. Epub 2006 Dec 6.17156835
108 McEwen MM, Pasvogel A, Murdaugh C. Effects of a Family-Based Diabetes Intervention on Family Social Capital Outcomes for Mexican American Adults. Diabetes Educ. Jun 2019;45(3):272–286. doi:10.1177/0145721719837899. Epub 2019 Mar 21.30895881
109 McKay RB, Levine DM, Bone LR. Community organization in a school health education program to reduce sodium consumption. The Journal of school health. Nov 1985 1985;55(9):364–6. doi:10.1111/j.1746-1561.1985.tb04149.x 3853041
110 Mead EL, Gittelsohn J, Roache C, Corriveau A, Sharma S. A community-based, environmental chronic disease prevention intervention to improve healthy eating psychosocial factors and behaviors in indigenous populations in the Canadian Arctic. Health Educ Behav. Oct 2013;40(5):592–602. doi:10.1177/1090198112467793. Epub 2012 Dec 13.23239767
111 Millard AV, Graham MA, Wang X, Pilot of a diabetes primary prevention program in a hard-to-reach, low-income, immigrant Hispanic population. J Immigr Minor Health. Oct 2011;13(5):906–13. doi:10.1007/s10903-010-9412-y.21061063
112 Mirza NM, Palmer MG, Sinclair KB, Effects of a low glycemic load or a low-fat dietary intervention on body weight in obese Hispanic American children and adolescents: a randomized controlled trial. Am J Clin Nutr. Feb 2013;97(2):276–85. doi:10.3945/ajcn.112.042630. Epub 2012 Dec 19.23255569
113 Mylant M, Isaacson MJ, Heil J. The Feasibility of the Strengthening Family and an Adapted American Indian Nutrition and Physical Activity Program: A Pilot Study. S D Med. Apr 2021;74(4):172–180.34432963
114 Napolitano MA, Harrington CB, Patchen L, Feasibility of a Digital Intervention to Promote Healthy Weight Management among Postpartum African American/Black Women. Int J Environ Res Public Health. Feb 23 2021;18(4)doi:10.3390/ijerph18042178.
115 Narayan KM, Hoskin M, Kozak D, Randomized clinical trial of lifestyle interventions in Pima Indians: a pilot study. Diabetic medicine: a journal of the British Diabetic Association. Jan 1998 1998;15(1):66–72. doi:10.1002/(SICI)1096-9136(199801)15:1<66::AID-DIA515>3.0.CO;2-A 9472866
116 Novotny R, Davis J, Butel J, Effect of the Children's Healthy Living Program on Young Child Overweight, Obesity, and Acanthosis Nigricans in the US-Affiliated Pacific Region: A Randomized Clinical Trial. JAMA Netw Open. Oct 5 2018;1(6):e183896. doi:10.1001/jamanetworkopen.2018.3896.30646266
117 Olvera N, Bush JA, Sharma SV, Knox BB, Scherer RL, Butte NF. BOUNCE: a community-based mother-daughter healthy lifestyle intervention for low-income Latino families. Obesity (Silver Spring). Feb 2010;18 Suppl 1:S102–4. doi:10.1038/oby.2009.439.
118 Pakseresht M, Kolahdooz F, Gittelsohn J, Roache C, Corriveau A, Sharma S. Improving vitamin A and D intake among Inuit and Inuvialuit in Arctic Canada: evidence from the Healthy Foods North study. J Epidemiol Community Health. May 2015;69(5):453–9. doi:10.1136/jech-2014-204623. Epub 2014 Dec 19.25527784
119 Palnati M, Marcus BH, Pekow P, Rosal MC, Manson JE, Chasan-Taber L. The Impact of a Lifestyle Intervention on Postpartum Weight Retention Among At-Risk Hispanic Women. Am J Prev Med. Jul 2021;61(1):44–54. doi:10.1016/j.amepre.2021.02.005. Epub 2021 May 13.33994252
120 Parra-Medina D, Wilcox S, Salinas J, Results of the Heart Healthy and Ethnically Relevant Lifestyle trial: a cardiovascular risk reduction intervention for African American women attending community health centers. Am J Public Health. Oct 2011;101(10):1914–21. doi:10.2105/AJPH.2011.300151. Epub 2011 Aug 18.21852629
121 Paskett ED, Baltic RD, Young GS, A Group Randomized Trial to Reduce Obesity among Appalachian Church Members: The Walk by Faith Study. Cancer Epidemiol Biomarkers Prev. Nov 2018;27(11):1289–1297. doi:10.1158/1055-9965.EPI-17-1085. Epub 2018 Oct 18.30337343
122 Perry AC, Flanagan EW, Velasquez C, Bolon KD, Zito GC, Ahn S. The Effects of a Science-Based Community Intervention on Health Outcomes in Minority Children: The Translational Health in Nutrition and Kinesiology Program. J Phys Act Health. Sep 1 2021;18(9):1074–1081. doi:10.1123/jpah.2020-0622. Print 2021 Sep 1.34172591
123 Prado G, Fernandez A, St George SM, Results of a Family-Based Intervention Promoting Healthy Weight Strategies in Overweight Hispanic Adolescents and Parents: An RCT. Am J Prev Med. Nov 2020;59(5):658–668. doi:10.1016/j.amepre.2020.06.010. Epub 2020 Oct 1.33011010
124 Ralston PA, Wickrama K, Coccia CC, Lemacks JL, Young-Clark IM, Ilich JZ. Health for Hearts United Longitudinal Trial: Improving Dietary Behaviors in Older African Americans. Am J Prev Med. Mar 2020;58(3):361–369. doi:10.1016/j.amepre.2019.09.024 31866211
125 Raman A, Ritchie LD, Lustig RH, Fitch MD, Hudes ML, Fleming SE. Insulin resistance is improved in overweight African American boys but not in girls following a one-year multidisciplinary community intervention program. J Pediatr Endocrinol Metab. Jan-Feb 2010;23(1–2):109–20. doi:10.1515/jpem.2010.23.1-2.109.20432814
126 Redmond LC, Jock B, Kolahdooz F, A multi-level, multi-component obesity intervention (Obesity Prevention and Evaluation of InterVention Effectiveness in NaTive North Americans) decreases soda intake in Native American adults. Public Health Nutr. Nov 29 2021;25(3):1–11. doi:10.1017/S1368980020001172.
127 Redmond LC, Wensel CR, Estradé M, Dietary Outcomes of a Multilevel, Multicomponent, Cluster Randomized Obesity Intervention in 6 Native American Communities in the Upper Midwest and Southwest United States. Curr Dev Nutr. Jun 2023;7(6):100043. doi:10.1016/j.cdnut.2023.100043. eCollection 2023 Jun.37396963
128 Resnicow K, Campbell M, Carr C, Body and soul. A dietary intervention conducted through African-American churches. Am J Prev Med. Aug 2004;27(2):97–105. doi:10.1016/j.amepre.2004.04.009.15261895
129 Resnicow K, Jackson A, Blissett D, Results of the healthy body healthy spirit trial. Health Psychol. Jul 2005;24(4):339–48. doi:10.1037/0278-6133.24.4.339.16045368
130 Resnicow K, Taylor R, Baskin M, McCarty F. Results of go girls: a weight control program for overweight African-American adolescent females. Obes Res. Oct 2005;13(10):1739–48. doi:10.1038/oby.2005.212.16286521
131 Risica PM, Gans KM, Kumanyika S, Kirtania U, Lasater TM. SisterTalk: final results of a culturally tailored cable television delivered weight control program for Black women. Int J Behav Nutr Phys Act. Dec 27 2013;10:141. doi:10.1186/1479-5868-10-141.24373253
132 Ronsley R, Lee AS, Kuzeljevic B, Panagiotopoulos C. Healthy Buddies™ reduces body mass index z-score and waist circumference in Aboriginal children living in remote coastal communities. J Sch Health. Sep 2013;83(9):605–13. doi:10.1111/josh.12072.23879779
133 Rosas LG, Vasquez JJ, Hedlin HK, Comparing enhanced versus standard Diabetes Prevention Program among indigenous adults in an urban setting: a randomized controlled trial. BMC Public Health. Jan 30 2020;20(1):139.32000738
134 Rosas LG, Lv N, Xiao L, Effect of a Culturally Adapted Behavioral Intervention for Latino Adults on Weight Loss Over 2 Years: A Randomized Clinical Trial. JAMA Netw Open. Dec 1 2020;3(12):e2027744. doi:10.1001/jamanetworkopen.2020.27744.33337491
135 Sadeghi B, Kaiser LL, Hanbury MM, A three-year multifaceted intervention to prevent obesity in children of Mexican-heritage. BMC Public Health. May 16 2019;19(1):582. doi:10.1186/s12889-019-6897-8.31096944
136 Salihu HM, Adegoke KK, Das R, Community-based fortified dietary intervention improved health outcomes among low-income African-American women. Nutr Res. Aug 2016;36(8):771–9. doi:10.1016/j.nutres.2016.04.006. Epub 2016 Apr 22.27440531
137 Sauder KA, Dabelea D, Bailey-Callahan R, Targeting risk factors for type 2 diabetes in American Indian youth: the Tribal Turning Point pilot study. Pediatr Obes. May 2018;13(5):321–329. doi:10.1111/ijpo.12223. Epub 2017 Jun 21.28635082
138 Scarinci IC, Moore A, Wynn-Wallace T, Cherrington A, Fouad M, Li Y. A community-based, culturally relevant intervention to promote healthy eating and physical activity among middle-aged African American women in rural Alabama: findings from a group randomized controlled trial. Prev Med. Dec 2014;69:13–20. doi:10.1016/j.ypmed.2014.08.016. Epub 2014 Aug 23.25152504
139 Scarinci IC, Hansen B, Kim YI. A Cluster-Randomized Controlled Trial to Evaluate a Community-Based Healthy Eating and Nutrition Label Interpretation Intervention Among Latinx Immigrant Mothers and Their Daughters. J Community Health. Apr 2021;46(2):313–323. doi:10.1007/s10900-020-00885-x.32671515
140 Shaikh AR, Vinokur AD, Yaroch AL, Williams GC, Resnicow K. Direct and mediated effects of two theoretically based interventions to increase consumption of fruits and vegetables in the Healthy Body Healthy Spirit trial. Health Educ Behav. Oct 2011;38(5):492–501. doi:10.1177/1090198110384468. Epub 2011 May 19.21596903
141 Sharma S, Fleming SE. One-year change in energy and macronutrient intakes of overweight and obese inner-city African American children: effect of community-based Taking Action Together type 2 diabetes prevention program. Eat Behav. Aug 2012;13(3):271–4. doi:10.1016/j.eatbeh.2012.03.003. Epub 2012 Mar 29.22664410
142 Soltero EG, Olson ML, Williams AN, Effects of a Community-Based Diabetes Prevention Program for Latino Youth with Obesity: A Randomized Controlled Trial. Obesity (Silver Spring). Dec 2018;26(12):1856–1865. doi:10.1002/oby.22300. Epub 2018 Nov 14.30426694
143 Sorkin DH, Mavandadi S, Rook KS, Dyadic collaboration in shared health behavior change: the effects of a randomized trial to test a lifestyle intervention for high-risk Latinas. Health Psychol. Jun 2014;33(6):566–75. doi:10.1037/hea0000063.24884910
144 Staffileno BA, Tangney CC, Fogg L. Favorable Outcomes Using an eHealth Approach to Promote Physical Activity and Nutrition Among Young African American Women. J Cardiovasc Nurs. Jan/Feb 2018;33(1):62–71. doi:10.1097/JCN.0000000000000409.28481823
145 Staten LK, Gregory-Mercado KY, Ranger-Moore J, Provider counseling, health education, and community health workers: the Arizona WISEWOMAN project. J Womens Health (Larchmt). Jun 2004;13(5):547–56. doi:10.1089/1540999041281133.15257846
146 Stolley MR, Fitzgibbon ML. Effects of an obesity prevention program on the eating behavior of African American mothers and daughters. Health education & behavior: the official publication of the Society for Public Health Education. Apr 1997 1997;24(2):152–64. doi:10.1177/109019819702400204 9079575
147 Stolley MR, Fitzgibbon ML, Schiffer L, Obesity reduction black intervention trial (ORBIT): six-month results. Obesity (Silver Spring). Jan 2009;17(1):100–6. doi:10.1038/oby.2008.488. Epub 2008 Nov 6.18997671
148 Story M, Sherwood NE, Himes JH, An after-school obesity prevention program for African-American girls: the Minnesota GEMS pilot study. Ethn Dis. Winter 2003;13(1 Suppl 1):S54–64.
149 Sun A, Cheng J, Bui Q, Liang Y, Ng T, Chen JL. Home-Based and Technology-Centered Childhood Obesity Prevention for Chinese Mothers With Preschool-Aged Children. J Transcult Nurs. Nov 2017;28(6):616–624. doi:10.1177/1043659617719139. Epub 2017 Jul 8.28826348
150 Taniguchi T, Haslam A, Sun W, Sisk M, Hayman J, Jernigan VBB. Impact of a Farm-to-School Nutrition and Gardening Intervention for Native American Families from the FRESH Study: A Randomized Wait-List Controlled Trial. Nutrients. Jun 23 2022;14(13)doi:10.3390/nu14132601.
151 Teran-Garcia M, Hammons AJ, Olvera N, Randomized control trial of a childhood obesity prevention family-based program: "Abriendo Caminos" and effects on BMI. Front Pediatr. 2023;11:1137825. doi:10.3389/fped.2023.1137825. eCollection 2023.37351320
152 Thompson JL, Allen P, Helitzer DL, Reducing diabetes risk in American Indian women. Am J Prev Med. Mar 2008;34(3):192–201. doi:10.1016/j.amepre.2007.11.014.18312806
153 Thompson D, Mirabile Y, Islam N, Diet Quality among Pre-Adolescent African American Girls in a Randomized Controlled Obesity Prevention Intervention Trial. Nutrients. Jun 12 2023;15(12)doi:10.3390/nu15122716.
154 Tomayko EJ, Prince RJ, Cronin KA, Adams AK. The Healthy Children, Strong Families intervention promotes improvements in nutrition, activity and body weight in American Indian families with young children. Public Health Nutr. Oct 2016;19(15):2850–9. doi:10.1017/S1368980016001014. Epub 2016 May 23.27211525
155 Tomayko EJ, Prince RJ, Cronin KA, Kim K, Parker T, Adams AK. The Healthy Children, Strong Families 2 (HCSF2) Randomized Controlled Trial Improved Healthy Behaviors in American Indian Families with Young Children. Curr Dev Nutr. Aug 2019;3(Suppl 2):53–62. doi:10.1093/cdn/nzy087. eCollection 2019 Aug.31453428
156 Tovar A, Fox K, Gans KM, Results from the Strong Families Start at Home/Familias Fuertes Comienzan en Casa: feasibility randomised control trial to improve the diet quality of low-income, predominantly Hispanic/Latinx children. Public Health Nutr. Jan 24 2023;26(4):1–15. doi:10.1017/S1368980023000174.36213951
157 Trude ACB, Surkan PJ, Cheskin LJ, Gittelsohn J. A multilevel, multicomponent childhood obesity prevention group-randomized controlled trial improves healthier food purchasing and reduces sweet-snack consumption among low-income African-American youth. Nutr J. Oct 29 2018;17(1):96. doi:10.1186/s12937-018-0406-2.30373597
158 Trude AC, Surkan PJ, Anderson Steeves E, Pollack Porter K, Gittelsohn J. The impact of a multilevel childhood obesity prevention intervention on healthful food acquisition, preparation, and fruit and vegetable consumption on African-American adult caregivers. Public Health Nutr. May 2019;22(7):1300–1315. doi:10.1017/S1368980018003038. Epub 2018 Nov 22.30463637
159 Tucker CM, Smith TM, Wippold GM, Impact of a University-Community Partnership Approach to Improving Health Behaviors and Outcomes Among Overweight/Obese Hispanic Adults. Am J Lifestyle Med. Nov-Dec 2017;11(6):479–488. doi:10.1177/1559827615623773. eCollection 2017 Nov-Dec.30202374
160 Tucker CM, Wippold GM, Williams JL, Arthur TM, Desmond FF, Robinson KC. A CBPR Study to Test the Impact of a Church-Based Health Empowerment Program on Health Behaviors and Health Outcomes of Black Adult Churchgoers. J Racial Ethn Health Disparities. Feb 2017;4(1):70–78. doi:10.1007/s40615-015-0203-y. Epub 2016 Jan 29.26830631
161 Tucker K, Ingram M, Doubleday K, Results From La Vida Buena (The Good Life): A Quasi-Experimental Intervention of a Community Health Worker-Led Family-Based Childhood Obesity Program for Latino Children 5–8 Years of Age on the U.S.-Mexico Border. Health Promot Pract. Nov 2023;24(6):1196–1205. doi:10.1177/15248399221112691. Epub 2022 Dec 5.36468422
162 Turner-McGrievy GM, Wilcox S, Frongillo EA, Effect of a Plant-Based vs Omnivorous Soul Food Diet on Weight and Lipid Levels Among African American Adults: A Randomized Clinical Trial. JAMA Netw Open. Jan 3 2023;6(1):e2250626. doi:10.1001/jamanetworkopen.2022.50626.36633848
163 Van Name MA, Camp AW, Magenheimer EA, Effective Translation of an Intensive Lifestyle Intervention for Hispanic Women With Prediabetes in a Community Health Center Setting. Diabetes Care. Apr 2016;39(4):525–31. doi:10.2337/dc15-1899. Epub 2016 Feb 23.26908915
164 Vincent D, McEwen MM, Hepworth JT, Stump CS. The effects of a community-based, culturally tailored diabetes prevention intervention for high-risk adults of Mexican descent. Diabetes Educ. Mar-Apr 2014;40(2):202–13. doi:10.1177/0145721714521020. Epub 2014 Feb 7.24510942
165 Vivian EM, Colbert LH, Remington PL. Lessons Learned from a Community Based Lifestyle Intervention for Youth at Risk for Type 2 Diabetes. J Obes Weight Loss Ther. Sep 13 2013;1doi:10.4172/2165-7904.1000191.
166 Wieland ML, Hanza MMM, Weis JA, Healthy Immigrant Families: Randomized Controlled Trial of a Family-Based Nutrition and Physical Activity Intervention. Am J Health Promot. Feb 2018;32(2):473–484. doi:10.1177/0890117117733342. Epub 2017 Nov 29.29186984
167 Wilcox S, Laken M, Bopp M, Increasing physical activity among church members: community-based participatory research. Am J Prev Med. Feb 2007;32(2):131–8. doi:10.1016/j.amepre.2006.10.009.17234487
168 Wilcox S, Parrott A, Baruth M, The Faith, Activity, and Nutrition program: a randomized controlled trial in African-American churches. Am J Prev Med. Feb 2013;44(2):122–31. doi:10.1016/j.amepre.2012.09.062.23332327
169 Wilcox S, Saunders RP, Kaczynski AT, Faith, Activity, and Nutrition Randomized Dissemination and Implementation Study: Countywide Adoption, Reach, and Effectiveness. Am J Prev Med. Jun 2018;54(6):776–785. doi:10.1016/j.amepre.2018.02.018. Epub 2018 Apr 12.29656913
170 Wilson DK, Sweeney AM, Van Horn ML, The Results of the Families Improving Together (FIT) for Weight Loss Randomized Trial in Overweight African American Adolescents. Ann Behav Med. Oct 3 2022;56(10):1042–1055. doi:10.1093/abm/kaab110.35226095
171 Witmer JM, Hensel MR, Holck PS, Ammerman AS, Will JC. Heart disease prevention for Alaska Native women: a review of pilot study findings. J Womens Health (Larchmt). Jun 2004;13(5):569–78. doi:10.1089/1540999041280981.15257848
172 Woods G, Levinson AH, Jones G, The Living Well by Faith Health and wellness program for African Americans: an exemplar of community-based participatory research. Ethn Dis. Spring 2013;23(2):223–9.
173 Wright K, Norris K, Newman Giger J, Suro Z. Improving healthy dietary behaviors, nutrition knowledge, and self-efficacy among underserved school children with parent and community involvement. Child Obes. Aug 2012;8(4):347–56. doi:10.1089/chi.2012.0045.22867074
174 Wright K, Giger JN, Norris K, Suro Z. Impact of a nurse-directed, coordinated school health program to enhance physical activity behaviors and reduce body mass index among minority children: a parallel-group, randomized control trial. Int J Nurs Stud. Jun 2013;50(6):727–37. doi:10.1016/j.ijnurstu.2012.09.004. Epub 2012 Sep 27.23021318
175 Yancey AK, McCarthy WJ, Harrison GG, Wong WK, Siegel JM, Leslie J. Challenges in improving fitness: results of a community-based, randomized, controlled lifestyle change intervention. J Womens Health (Larchmt). May 2006;15(4):412–29. doi:10.1089/jwh.2006.15.412.16724889
176 Yeh MC, Heo M, Suchday S, Translation of the Diabetes Prevention Program for diabetes risk reduction in Chinese immigrants in New York City. Diabet Med. Apr 2016;33(4):547–51. doi:10.1111/dme.12848. Epub 2015 Aug 18.26179569
177 Yin Z, Parra-Medina D, Cordova A, Míranos! Look at us, we are healthy! An environmental approach to early childhood obesity prevention. Child Obes. Oct 2012;8(5):429–39. doi:10.1089/chi.2012.0125.23061498
178 Yin Z, Liang Y, Howard JT, ¡Míranos! a Comprehensive Preschool Obesity Prevention Program in Low-Income Latino Children: One-year Results of a Clustered Randomized Controlled Trial. Public Health Nutr. Nov 11 2022:1–26. doi:10.1017/S1368980022002439.