# Methods

The Committee used NESR’s methodology to conduct this evidence scan. A NESR evidence scan is an exploratory evidence description project in which systematic methods are used to search for and describe the volume and characteristics of evidence available on a nutrition question or topic of public health importance. NESR evidence scans involve the following: development/refinement of the research question, protocol development, searching for and screening studies, minimal data extraction, and description of evidence. NESR evidence scans do not include: data extraction of study results, risk of bias assessment, synthesis of the evidence, development of conclusion statements, or grading the strength of the evidence.

NESR’s evidence scan methodology is described in detail in its methodology manual,^*^ as well as in the Committee’s scientific report.^†^ This section presents an overview of the specific methods used to answer the evidence scan question: What evidence has been published on the relationship between culturally tailored dietary interventions and diet-related psychosocial factors, dietary intake, diet quality, and health outcomes?

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

## Develop a protocol

An evidence scan protocol is the plan for how NESR’s methodology will be used to conduct a specific evidence scan and is established by the Committee, a priori, before any evidence is reviewed. The protocol is designed to capture the most appropriate and relevant body of evidence to answer the evidence scan question. Development of the protocol involves discussion of the strengths and limitations of various methodological approaches relevant to the question, which then inform subsequent steps of the evidence scan process. The protocol describes all of the methods that will be used throughout the evidence scan process. Additionally, the protocol includes the following components, which are tailored to each evidence scan question: the analytic framework, the inclusion and exclusion criteria, and the evidence description plan.

The protocol was posted online (https://nesr.usda.gov/protocols) for the public to view and comment on.

## Develop an analytic framework

An analytic framework visually represents the overall scope of the evidence scan question and depicts the contributing elements that were examined and evaluated. Figure 1 is the analytic framework for the evidence scan. The interventions of interest were those that have been culturally tailored, modified, or adapted to alter intake of foods in children, adolescents, adults, older adults, and individuals during pregnancy and postpartum. The outcomes were:

- Diet-related psychosocial factors including food-related norms, attitudes, values, and self-efficacy;
- Dietary intake;
- Diet quality;
- Energy intake;
- Risk factors for cardiovascular disease, including cholesterol (high-density lipoprotein [HDL], low-density lipoprotein [LDL]), triglycerides, hyperlipidemia, blood pressure (systolic and diastolic), and hypertension;
- Risk factors for type 2 diabetes, including fasting blood glucose, fasting insulin, glucose tolerance/insulin resistance, hemoglobin A1c (HbA1c), and prediabetes in children, adolescents, adults, and older adults; and
- Growth, including height, weight, stunting, failure to thrive, wasting, BMI-for-age, body circumferences (arm, neck, thigh) in children and adolescents; Body composition, including skinfold thickness, fat mass, ectopic fat, fat-free mass or lean mass, waist circumference, waist-to-hip-ratio in children, adolescents, adults, older adults; Risk of obesity, including BMI, underweight, normal weight, overweight and/or obesity in children, adolescents, adults, older adults, and weight gain, and weight loss and maintenance in adults and older adults; Pregnancy and postpartum-related weight change, including adequacy of total gestational weight gain (i.e., in relation to recommendations based on pre-pregnancy BMI) and postpartum weight change in individuals during pregnancy or postpartum.

Figure 1 Analytic framework for the evidence scan question: What evidence has been published on the relationship between culturally tailored dietary interventions and diet-related psychosocial factors, dietary intake, diet quality, and health outcomes?

Population | Intervention | Outcome
Children and adolescents (2 up to 19 years) | Interventions that have been culturally tailored, modified, or adapted to alter intake of foods | Diet-related psychosocial factors, including food-related norms, attitudes, values, and self-efficacy; Dietary intake; Diet quality; Energy intake; Risk of cardiovascular disease; - HDL cholesterol; - LDL cholesterol; - Triglycerides; - Hyperlipidemia; - Blood pressure (systolic, diastolic); - Hypertension; Risk of type 2 diabetes; - Fasting blood glucose; - Fasting insulin; - Glucose tolerance/insulin resistance; - HbA1C; - Prediabetes; Growth (in children and adolescents); - Height; - Weight; - Stunting, failure to thrive, wasting; - BMI-for-age; - Body circumference (arm, neck, thigh); Body composition (in children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass or lean mass; - Waist circumference, waist-to-hip-ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Underweight; - Normal weight; - Overweight and/or obesity; - Weight gain; - Weight loss and maintenance (adults and older adults only)
Adults and older adults (19 years and older) | Interventions that have been culturally tailored, modified, or adapted to alter intake of foods
Individuals during pregnancy and postpartum | Interventions that have been culturally tailored, modified, or adapted to alter intake of foods | Diet-related psychosocial factors, dietary intake, diet quality, and energy intake as described above.; Pregnancy and postpartum-related weight change; - Gestational weight gain; - Postpartum weight change

## Develop inclusion and exclusion criteria

The inclusion and exclusion criteria provide an objective, consistent, and transparent framework for determining which articles to include in the evidence scan (Table 2). These criteria ensure that the most relevant and appropriate body of evidence is identified for the evidence scan question, and that the evidence reviewed is:^*^

- Applicable to the U.S. population of interest
- Relevant to Federal public health nutrition policies and programs
- Rigorous from a scientific perspective

* USDA Nutrition Evidence Systematic Review Branch. USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

Table 2 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials^†^; † Including quasi-experimental and controlled before-and-after studies | - Uncontrolled trials^‡^; ‡ Including uncontrolled before-and-after studies; - Case-control studies; - Cross-sectional studies; - Ecological studies; - Narrative reviews; - Systematic reviews; - Meta-analyses; - Modeling and simulation studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies
Publication date | - January 1980 – September 2023 | - Before January 1980; after September 2023
Country | - Studies conducted in the United States and/or Canada | - Studies conducted outside of the United States or Canada
Population: Study participants | - Human; - People living in the United States or Canada | - Non-human; - People living outside of the United States or Canada
Population: Life stage | Diet-related psychosocial factors; dietary intake; diet quality; energy intake; growth, body composition, and risk of obesity:; - At intervention and outcome:; ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older); ○ Individuals during pregnancy; ○ Individuals during postpartum; Risk of cardiovascular disease and Risk of type 2 diabetes:; - At intervention and outcome:; ○ Children and adolescents (2 up to 19 years); ○ Adults and older adults (19 years and older); - At intervention:; ○ Individuals during pregnancy; ○ Individuals during postpartum | At intervention and outcome:; - Infants and young children (birth up to 24 months); Risk of cardiovascular disease and Risk of type 2 diabetes:; - At outcome:; ○ Individuals during pregnancy; ○ Individuals during postpartum
Population: Health status | - Studies that [underlined: exclusively] enroll participants not diagnosed with a disease^*^; * Studies that enroll participants who are at risk for chronic disease were included; - Studies that enroll [underlined: some] participants:; ○ diagnosed with a disease;; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ who became pregnant using Assisted Reproductive Technologies;; ○ with multiple gestation pregnancies;; ○ receiving pharmacotherapy to treat obesity;; ○ pre- or post-bariatric surgery;; ○ and/or hospitalized for an illness, injury, or surgery | - Studies that [underlined: exclusively] enroll participants:; ○ diagnosed with a disease;^†^; † Studies that exclusively enroll participants with obesity were included; ○ with severe undernutrition, failure to thrive/underweight, stunting, or wasting;; ○ who became pregnant using Assisted Reproductive Technologies;; ○ with multiple gestation pregnancies;; ○ receiving pharmacotherapy to treat obesity;; ○ pre- or post-bariatric surgery;; ○ and/or hospitalized for an illness, injury, or surgery^‡^; ‡ Studies that exclusively enroll participants post-cesarean section were included
Intervention | - Interventions that have been culturally tailored, modified, or adapted to alter intake of foods | - Studies with interventions that have not been culturally tailored, modified, or adapted; - Studies with interventions that change consumption of a single food
Comparator | N/A | - No comparator
Outcomes | Diet-related psychosocial factors, including food-related norms, attitudes, values, and self-efficacy; Dietary intake assessed by intake of foods or food group(s); Diet quality Energy intake; Risk of cardiovascular disease; - LDL cholesterol; - HDL cholesterol; - Triglycerides; - Hyperlipidemia; - Blood pressure (systolic, diastolic); - Hypertension; Risk of type 2 diabetes; - Fasting blood glucose; - Fasting insulin; - Glucose tolerance/insulin resistance; - HbA1C; - Prediabetes; Growth (in children, adolescents); - Height; - Weight; - Stunting, failure to thrive, wasting; - BMI-for-age; - Body circumferences (arm, neck, thigh); Body composition (in children, adolescents, adults, older adults); - Skinfold thickness; - Fat mass, ectopic fat; - Fat-free mass, lean mass; - Waist circumference, waist-to-hip ratio; Risk of obesity (in children, adolescents, adults, older adults); - BMI; - Underweight; - Normal weight; - Overweight and/or obesity; - Weight gain; - Weight loss and maintenance (in adults, older adults); Pregnancy- and postpartum-related weight change (individuals during pregnancy or postpartum); - Adequacy of total gestational weight gain (i.e., in relation to recommendations based on pre-pregnancy BMI); - Postpartum weight change | - Dietary intake assessed only by intake of individual nutrient(s); - Urinary measures of glucose; - Non-fasting blood glucose; - Non-fasting insulin; - Gestational weight gain only during certain time periods or trimesters of pregnancy; - Absolute total gestational weight gain (i.e., not in relation to recommendations based on pre-pregnancy BMI); - Weight loss that is specifically classified as unintentional weight loss (e.g., a component of frailty)
Publication status | - Peer-reviewed articles published in research journals | - Non-peer-reviewed articles, unpublished data or manuscripts, pre-prints, reports, editorials, retracted articles, and conference abstracts or proceedings
Language | - Published in English | - Not published in English

## Search for and screen studies

NESR librarians, in collaboration with NESR analysts and the Committee, used the analytic framework and inclusion and exclusion criteria to develop a comprehensive literature search strategy. The literature search strategy included selecting and searching the appropriate bibliographic databases, translating search using syntax appropriate for the databases being searched, and employing search refinements, such as search filters. In this evidence scan, the search was limited to one database (PubMed). The full literature search is documented in Appendix 2.

The screening of electronic database search results was facilitated using a web-based tool (DistillerSR, DistillerSR Inc., Ottawa, Ontario, Canada). After removal of duplicates, a re-ranking function was utilized in DistillerSR to reorder articles by relevancy. Two NESR analysts independently screened titles of search results up to a 93% recall rate of citations eligible for abstract screening (goal recall rate: 90%), as assessed by DistillerSR’s natural language processing capabilities. NESR analysts stopped screening remaining titles of citations past this 93% recall rate. Two NESR analysts independently performed abstract and full-text screening to determine which articles met the inclusion criteria. Differences in screening decisions were resolved by consultation with a third NESR analyst. A manual search to find peer-reviewed published articles not identified through the electronic database search was not conducted.

## Extract data

NESR analysts extracted the most essential data from each included article to describe key characteristics of the available evidence, such as the author, publication year, study design, population life stage, intervention, approach and methods for cultural tailoring, comparator, and outcomes. One NESR analyst extracted the data and a second NESR analyst reviewed the extracted data for accuracy.

## Describe the evidence

The Committee described the evidence from all included studies to answer the evidence scan question. The description of the evidence includes a detailed summary of the volume and characteristics (population, intervention, outcome) of the included evidence. The evidence is described and presented in text, figures, and tables.

## Recommend future research and considerations for future review projects

The Committee identified and documented research gaps and methodological limitations throughout the evidence scan process. These gaps and limitations were used to develop research recommendations and considerations for future work that may strengthen and build on the body of evidence. In addition, the Committee noted several considerations for future review projects that could be conducted on this topic.

## Health equity considerations

The Committee was charged by HHS and USDA to review all scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds. The Committee made a number of health equity considerations throughout the NESR evidence scan process. The Committee’s Scientific Report^*^ includes a more detailed discussion of their approach to applying a health equity lens to their review of evidence, but examples of how the Committee incorporated health equity considerations into this evidence scan include assessing the cultural sensitivity of intervention techniques and reviewing the degree of community involvement in intervention design and implementation.

* 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025