# Introduction

To prepare for the development of the Dietary Guidelines for Americans, 2025-2030, the U.S. Departments of Health and Human Services (HHS) (Appendix 1) and Agriculture (USDA) identified a proposed list of scientific questions based on relevance, importance, potential federal impact, and avoiding duplication, which were posted for public comment.^*^ The Departments appointed the 2025 Dietary Guidelines Advisory Committee (Committee) in January 2023 to review evidence on the scientific questions. The Committee’s review of the evidence forms the basis of the Scientific Report of the 2025 Dietary Guidelines Advisory Committee,^†^ which includes independent, science-based advice and recommendations to HHS and USDA and is considered during the development of the next edition of the Dietary Guidelines. In addition, the Committee was asked to review all of the scientific questions with a health equity lens to ensure that the next edition of the Dietary Guidelines is relevant to people with diverse racial, ethnic, socioeconomic, and cultural backgrounds.

* Dietary Guidelines for Americans: Learn About the Process. 2022. Available at: https://www.dietaryguidelines.gov/work-underway/learn-about-process

† 2025 Dietary Guidelines Advisory Committee. 2024. Scientific Report of the 2025 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Health and Human Services and Secretary of Agriculture. U.S. Department of Health and Human Services. 10.52570/DGAC2025

Federal data show that Americans fall short of meeting Dietary Guidelines recommendations, and diet-related chronic disease rates have risen to pervasive levels and continue to be a major public health concern. Therefore, when refining and prioritizing scientific questions, the Committee expressed interest in understanding food-based strategies that can improve adherence to the Dietary Guidelines, particularly among diverse populations. For example, the Dietary Guidelines for Americans, 2020–2025 includes the following key recommendation: “Customize and enjoy nutrient-dense food and beverage choices to reflect personal preferences, cultural traditions, and budgetary considerations.”^‡^ Culturally tailored dietary interventions have been conducted that are designed to align with specific cultural practices, beliefs, and preferences of the target population, with the aim of improving the quality of their diet and health outcomes. However, the breadth of these interventions in the scientific literature is unclear at this time.

‡ U.S. Department of Agriculture and U.S. Department of Health and Human Services. Dietary Guidelines for Americans, 2020-2025. 9th Edition. December 2020. Available at: DietaryGuidelines.gov.

As such, the following scientific question was prioritized: What evidence has been published on the relationship between culturally tailored dietary interventions and diet-related psychosocial factors, dietary intake, diet quality, and health outcomes? The Committee conducted an evidence scan to address these research needs, in collaboration with USDA’s Nutrition Evidence Systematic Review (NESR) team (Table 1).

Table 1 Evidence scan history

Date | Description | Citation
October 2023 | Evidence scan protocol for the 2025 Dietary Guidelines Advisory Committee published online | Palacios C, Anderson CAM, Andres A, Fisher JO, Gardner CD, Giovannucci E, Hoelscher DM, Jernigan VBB, Odoms-Young A, Raynor HA, Stanford FC, Obbagy J, Callahan EH, Cole NC, Fultz A, Kingshipp BJ, Webster A, Higgins M, Butera G, Terry N. Culturally Tailored Dietary Interventions and Diet-Related Psychosocial Factors, Dietary Intake, Diet Quality, and Health Outcomes: An Evidence Scan Protocol. September 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/protocols