# Plain language summary

### What is the question?

The question is: What evidence has been published on the relationship between culturally tailored dietary interventions and diet-related psychosocial factors, dietary intake, diet quality, and health outcomes? The populations of interest for this question include children, adolescents, adults, older adults, and individuals during pregnancy and postpartum.

### Why was this question asked?

This evidence scan was conducted by the 2025 Dietary Guidelines Advisory Committee as part of the process to develop the Dietary Guidelines for Americans, 2025–2030.

### How was this question answered?

The Committee conducted an evidence scan to answer this question with support from the USDA Nutrition Evidence Systematic Review team.

### What is the answer to the question?

The body of evidence included 178 articles. Most articles were in adults and included both male and female participants. The most frequently assessed outcomes were growth, body composition, and risk of obesity and dietary intake. Many different strategies were used to culturally tailor the interventions; common examples included translating materials into the native language of participants and including community members in designing and implementing the studies. Most articles received funding from the United States or Canadian government.

### How up-to-date is this evidence scan?

This evidence scan is based on articles published between January 1980 and September 2023.