# Acknowledgments and funding

The Committee members were involved in: establishing all aspects of the protocol, which presented the plan for how they planned to examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; and deliberating on the body of evidence for each question. The NESR team, with assistance from Federal Liaisons and Project Leadership, supported the Committee by facilitating, executing, and documenting the work necessary to ensure the evidence scan was completed in accordance with NESR methodology.

The Committee and NESR staff thank Federal staff from HHS and USDA (Meghan Adler, MS, RDN; Dana DeSilva, PhD, RD; Rachel Inman, MS, RD; Sarah Karp, MNSP, RD, LDN; Emily Levin, MPH, RDN; Chinwe Obudulu, MS, RD, LD; Elizabeth Rahavi, RD) and Project Leadership (HHS: Janet de Jesus, MS, RD; USDA: Eve Stoody, PhD) for their support throughout this work.