# Appendix 4 Supplementary figures

Figure A 1 describes the number of articles that included a given outcome, plotted against racial and/or ethnic group.

Figure A 1 Articles by outcomes across racial and/or ethnic groups^a^

^a^ Abbreviations: CVD: cardiovascular disease; GBCO: growth, body composition, and risk of obesity; PPWC: postpartum weight change; T2D: type 2 diabetes mellitus

This figure shows a bubble chart of outcomes plotted against racial and/or ethnic group. For articles with Black, African American, or African descent participants (77 total articles), the number of articles reporting each outcome is: GBCO: 47 articles; dietary intake: 47 articles; risk of CVD: 23 articles; diet-related psychosocial factors: 18 articles; energy intake: 17 articles; risk of type 2 diabetes: 11 articles; diet quality: 13 articles; postpartum weight change: 3 articles. For articles with Hispanic or Latino participants (71 total articles), the number of articles reporting each outcome is: GBCO: 50 articles; dietary intake: 40 articles; risk of CVD: 19 articles; diet-related psychosocial factors: 11 articles; energy intake: 11 articles; risk of type 2 diabetes: 17 articles; diet quality: 5 articles; postpartum weight change: 1 article. For articles with American Indian, Alaska Native, or Indigenous participants (27 total articles), the number of articles reporting each outcome is: GBCO: 18 articles; dietary intake: 19 articles; risk of CVD: 9 articles; diet-related psychosocial factors: 14 articles; energy intake: 10 articles; risk of type 2 diabetes: 5 articles; diet quality: 6 articles; postpartum weight change: 0 articles. For articles with White participants (16 total articles), the number of articles reporting each outcome is: GBCO: 8 articles; dietary intake: 12 articles; risk of CVD: 6 articles; diet-related psychosocial factors: 2 articles; energy intake: 4 articles; risk of type 2 diabetes: 3 articles; diet quality: 2 articles; postpartum weight change: 1 article. For articles with Asian participants (11 total articles), the number of articles reporting each outcome is: GBCO: 11 articles; dietary intake: 4 articles; risk of CVD: 8 articles; diet-related psychosocial factors: 6 articles; energy intake: 1 article; risk of type 2 diabetes: 6 articles; diet quality: 1 article.

Figure A 2 describes the number of articles that included a given outcome, plotted against the degree of community involvement in intervention design.

Figure A 2 Articles by outcome and degree of community involvement in intervention design^a^

^a^ Abbreviations: CVD: cardiovascular disease; GBCO: growth, body composition, and risk of obesity; PPWC: postpartum weight change; T2D: type 2 diabetes mellitus

This figure shows a bubble chart of outcomes (plotted on the x-axis) plotted against level of community involvement in intervention design (on the y-axis): high involvement, some involvement, and no/not reported. Overall, the proportion of articles reporting each outcome was consistent across levels of community invovlement. For high community involvement, the number of articles reporting each outcome is as follows: GBCO: 50 articles; dietary intake: 46 articles; risk of CVD: 27 articles; diet-related psychosocial factors: 23 articles; energy intake: 15 articles; risk of type 2 diabetes: 15 articles; diet quality: 12 articles; postpartum weight change: 1 article. For some community involvement, the number of articles reporting each outcome is as follows: GBCO: 32 articles; dietary intake: 38 articles; risk of CVD: 9 articles; diet-related psychosocial factors: 12 articles; energy intake: 10 articles; risk of type 2 diabetes: 8 articles; diet quality: 8 articles; postpartum weight change: 0 articles. For no/not reported community involvement, the number of articles reporting each outcome is as follows: GBCO: 35 articles; dietary intake: 25 articles; risk of CVD: 16 articles; diet-related psychosocial factors: 15 articles; energy intake: 13 articles; risk of type 2 diabetes: 12 articles; diet quality: 3 articles; postpartum weight change: 3 articles.