# Appendix 3 Excluded articles

The following table (Table A 3) lists the articles excluded after full-text screening for this evidence scan question. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table A 3 Articles excluded after full-text screening

| Citation | Rationale
1 | Ahmed S, Dupuis V, Tyron M, Intended and Unintended Consequences of a Community-Based Fresh Fruit and Vegetable Dietary Intervention on the Flathead Reservation of the Confederated Salish and Kootenai Tribes. Front Public Health. 2020. 8:331. doi:10.3389/fpubh.2020.00331 32850578 | Study Design
2 | Akufo JK. Get up and Get Moving: a nutrition and physical activity after-school program for Latino adolescents of Erie Neighborhood House. J Prev Interv Community. 2022. 50:36–50. doi:10.1080/10852352.2021.1915734 35084289 | Study Design
3 | Allicock M, Johnson LS, Leone L, Promoting fruit and vegetable consumption among members of black churches, Michigan and North Carolina, 2008–2010. Prev Chronic Dis. 2013. 10:E33. doi:10.5888/pcd10.120161 23489638 | Study Design
4 | Anand SS, Samaan Z, Middleton C, A Digital Health Intervention to Lower Cardiovascular Risk: A Randomized Clinical Trial. JAMA Cardiol. 2016. 1:601–6. doi:10.1001/jamacardio.2016.1035 27438754 | Outcome
5 | Babatunde OT, Himburg SP, Newman FL, Campa A, Dixon Z. Theory-driven intervention improves calcium intake, osteoporosis knowledge, and self-efficacy in community-dwelling older Black adults. J Nutr Educ Behav. 2011. 43:434–40. doi:10.1016/j.jneb.2010.07.004 21531178 | Intervention not relevant; Single Food Intervention
6 | Baltaci A, Hurtado Choque GA, Davey C, Padres Preparados, Jóvenes Saludables: A Randomized Controlled Trial to Test Effects of a Community-Based Intervention on Latino Father's Parenting Practices. Nutrients. 2022. 14:4967. doi:10.3390/nu14234967 36500997 | Outcome
7 | Bangurah SS, Vardaman SA, Cleveland KK. Hypertension in the Faith Community: A Four-Week, Nurse Led, Diet/Exercise Intervention. J Christ Nurs. 2017. 34:225–231. doi:10.1097/cnj.0000000000000420 28902051 | Study Design; Health Status
8 | Barkin SL, Heerman WJ, Sommer EC, Effect of a Behavioral Intervention for Underserved Preschool-Age Children on Change in Body Mass Index: A Randomized Clinical Trial. Jama. 2018. 320:450–460. doi:10.1001/jama.2018.9128 30088008 | Intervention not relevant
9 | Barrera M, Toobert D, Strycker L, Osuna D. Effects of acculturation on a culturally adapted diabetes intervention for Latinas. Health Psychol. 2012. 31:51–4. doi:10.1037/a0025205 21859212 | Study Design; Health Status
10 | Bonnevie E, Morales O, Rosenberg SD, Evaluation of a campaign to reduce consumption of sugar-sweetened beverages in New Jersey. Prev Med. 2020. 136:106062. doi:10.1016/j.ypmed.2020.106062 32205177 | Study Design, Single Food Intervention
11 | Chen JL, Kwan M, Mac A, Chin NC, Liu K. iStart smart: a primary-care based and community partnered childhood obesity management program for Chinese-American children: feasibility study. J Immigr Minor Health. 2013. 15:1125–8. doi:10.1007/s10903-013-9830-8 23595264 | Study Design
12 | Cioffi CE, Ranjani H, Staimez LR, Anjana RM, Mohan V, Weber MB. Self-efficacy and diabetes prevention in overweight South Asians with pre-diabetes. BMJ Open Diabetes Res Care. 2018. 6:e000561. doi:10.1136/bmjdrc-2018-000561. | Country
13 | Clark DO, Keith N, Weiner M, Xu H. Outcomes of an RCT of videoconference vs. in-person or in-clinic nutrition and exercise in midlife adults with obesity. Obes Sci Pract. 2019. 5:111–119. doi:10.1002/osp4.318.31019728 | Study Design, Intervention not relevant
14 | Cohen JF, Kraak VI, Choumenkovitch SF, Hyatt RR, Economos CD. The CHANGE study: a healthy-lifestyles intervention to improve rural children's diet quality. J Acad Nutr Diet. 2014. 114:48–53. doi:10.1016/j.jand.2013.08.014.24126295 | Intervention not relevant
15 | Cooper KC, King MA, Sarpong DF. Tipping the scales on obesity: church-based health promotion for African American women. J Christ Nurs. 2015. 32:41–5. doi: 10.1097/CNJ.0000000000000132.25585468 | Study Design
16 | Davis SM, Clay T, Smyth M, Pathways curriculum and family interventions to promote healthful eating and physical activity in American Indian schoolchildren. Prev Med. 2003. 37:S24–34. doi:10.1016/j.ypmed.2003.08.011.14636806 | Outcome
17 | Davis SK, Quarells, R, Gibbons, GH. A comprehensive cardiovascular disease lifestyle treatment controlled trial among high-risk African Americans. Open J Prev Med. 2013. 3:526–533. doi:10.4236/ojpm.2013.39071 24955290 | Health Status
18 | Economos CD, Hyatt RR, Goldberg JP, A community intervention reduces BMI z-score in children: Shape Up Somerville first year results. Obesity (Silver Spring). 2007. 15:1325–36. doi:10.1038/oby.2007.155.17495210 | Intervention not relevant
19 | Economos CD, Hyatt RR, Must A, Shape Up Somerville two-year results: a community-based environmental change intervention sustains weight reduction in children. Prev Med. 2013. 57:322–7. doi:10.1016/j.ypmed.2013.06.001 23756187 | Intervention not relevant
20 | Ellis DA, Janisse H, Naar-King S, The effects of multisystemic therapy on family support for weight loss among obese African-American adolescents: findings from a randomized controlled trial. J Dev Behav Pediatr. 2010. 31:461–8. doi:10.1097/DBP.0b013e3181e35337 20585269 | Intervention not relevant
21 | Emmons KM, Stoddard AM, Fletcher R, Cancer prevention among working class, multiethnic adults: results of the healthy directions-health centers study. Am J Public Health. 2005. 95:1200–5. doi:10.2105/ajph.2004.038695 15933240 | Intervention not relevant
22 | Evans-Hudnall GL, Stanley MA, Clark AN, Improving secondary stroke self-care among underserved ethnic minority individuals: a randomized clinical trial of a pilot intervention. J Behav Med. 2014. 37:196–204. doi:10.1007/s10865-012-9469-2 23225167 | Health Status
23 | Falbe J, Friedman LE, Sokal-Gutierrez K, Thompson HR, Tantoco NK, Madsen KA. "She Gave Me the Confidence to Open Up": Bridging Communication by Promotoras in a Childhood Obesity Intervention for Latino Families. Health Educ Behav. 2017. 44:728–737. doi:10.1177/1090198117727323 28851237 | Study Design
24 | Fields S, Arthur K, Schueler J, Smallman R. Using a counterfactual-based intervention to change eating intentions: Results from Hispanic and non-Hispanic undergraduate and community samples. Appetite. 2023. 183:106460. doi:10.1016/j.appet.2023.106460 36642115 | Intervention not relevant
25 | Folta SC, Kuder JF, Goldberg JP, Changes in diet and physical activity resulting from the Shape Up Somerville community intervention. BMC Pediatr. 2013. 13:157. doi:10.1186/1471-2431-13-157 24093936 | Intervention not relevant
26 | Ford CN, Weber MB, Staimez LR, Dietary changes in a diabetes prevention intervention among people with prediabetes: the Diabetes Community Lifestyle Improvement Program trial. Acta Diabetol. 2019. 56:197–209. doi:10.1007/s00592-018-1249-1 30426214 | Intervention not relevant; Country
27 | Foreyt, JP, Ramirez, AG, Cousins, JH. Cuidando El Corazon--a weight-reduction intervention for Mexican Americans. Am J Clin Nutr. 1991. 53:1639s–1641s. doi:10.1093/ajcn/53.6.1639S .2031499 | Duplicate data
28 | Fritz H, Hu YL. Habit Formation Intervention to Reduce Frailty Risk Factors: A Feasibility Study. Am J Occup Ther. 2022. 76:7603205090. doi:10.5014/ajot.2022.045948 35616653 | Intervention not relevant
29 | Fulkerson JA, Friend S, Horning M, Family Home Food Environment and Nutrition-Related Parent and Child Personal and Behavioral Outcomes of the Healthy Home Offerings via the Mealtime Environment (HOME) Plus Program: A Randomized Controlled Trial. J Acad Nutr Diet. 2018. 118:240–251. doi:10.1016/j.jand.2017.04.006 28578900 | Intervention not relevant
30 | Goodman J, Blake J. Nutrition education: a computer-based education program. J Health Care Poor Underserved. 2005. 16:118–27. doi:10.1353/hpu.2005.0123 16327100 | Study Design
31 | Gunther C, Rogers C, Holloman C, Child diet and health outcomes of the simple suppers program: a 10-week, 2-group quasi-experimental family meals trial. BMC Public Health. 2019. 19:1657. doi:10.1186/s12889–019-7930-7 31823753 | Intervention not relevant
32 | Harrell TK, Davy BM, Stewart JL, King DS. Effectiveness of a school-based intervention to increase health knowledge of cardiovascular disease risk factors among rural Mississippi middle school children. South Med J. 2005. 98:1173–80. doi:10.1097/01.smj.0000182499.59715.07 16440917 | Intervention not relevant
33 | Heerman WJ, Cole J, Teeters L, Qualitative analysis of COACH: A community-based behavioral intervention to reduce obesity health disparities within a marginalized community. Contemp Clin Trials Commun. 2019. 16:100452. doi:10.1016/j.conctc.2019.100452 31650072 | Study Design; Outcome
34 | Henshaw MM, Borrelli B, Gregorich SE, Randomized Trial of Motivational Interviewing to Prevent Early Childhood Caries in Public Housing. JDR Clin Trans Res. 2018. 3:353–365. doi:10.1177/2380084418794377 30238060 | Intervention not relevant; Outcome
35 | Hoelscher DM, Springer AE, Ranjit N, Reductions in child obesity among disadvantaged school children with community involvement: the Travis County CATCH Trial. Obesity (Silver Spring). 2010. 18 Suppl 1:S36–44. doi:10.1038/oby.2009.430 20107459 | Study Design; Intervention not relevant
36 | Hopkins LC, Holloman C, Webster A, Caregiver Nutritional Health Outcomes of the Simple Suppers Study: Results from a 10 Week, Two-Group Quasi-Experimental Family Meals Intervention. Nutrients. 2022. 14:250. doi:10.3390/nu14020250 35057431 | Intervention not relevant
37 | Kaphingst KA, Lobb R, Fay ME, Impact of intervention dose on cancer-related health behaviors among working-class, multiethnic, community health center patients. Am J Health Promot. 2007. 21:262–6. doi:10.4278/0890-1171-21.4.262 17375492 | Study Design; Intervention not relevant
38 | Kelley MA. Culturally appropriate breast health educational intervention program for African-American women. J Natl Black Nurses Assoc. 2004. 15:36–47 15712819 | Intervention not relevant
39 | Kennedy BM, Champagne CM, Ryan DH, The "Rolling Store:" an economical and environmental approach to the prevention of weight gain in African American women. Ethn Dis. 2009. 19:7–12 19341156 | Intervention not relevant
40 | Kennedy BM, Ryan DH, Johnson WD, Baton Rouge Healthy Eating and Lifestyle Program (BR-HELP): A Pilot Health Promotion Program. J Prev Interv Community. 2015. 43:95–108. doi:10.1080/10852352.2014.973256 25898217 | Intervention not relevant
41 | Lee-Kwan SH, Bleich SN, Kim H, Colantuoni E, Gittelsohn J. Environmental Intervention in Carryout Restaurants Increases Sales of Healthy Menu Items in a Low-Income Urban Setting. Am J Health Promot. 2015. 29:357–64. doi:10.4278/ajhp.130805-QUAN-408 24968184 | Intervention not relevant; Outcome
42 | Lindberg NM, Stevens VJ, Vega-López S, Kauffman TL, Calderón MR, Cervantes MA. A weight-loss intervention program designed for Mexican-American women: cultural adaptations and results. J Immigr Minor Health. 2012. 14:1030–9. doi:10.1007/s10903-012-9616-4 22460538 | Study Design
43 | Ma GX, Bhimla A, Zhu L, Development of an Intervention to Promote Physical Activity and Reduce Dietary Sodium Intake for Preventing Hypertension and Chronic Disease in Filipino Americans. J Racial Ethn Health Disparities. 2021. 8:283–292. doi:10.1007/s40615-020-00781-z 32495306 | Single Food Intervention
44 | Magaña S, Li H, Miranda E, Paradiso de Sayu R. Improving health behaviours of Latina mothers of youths and adults with intellectual and developmental disabilities. J Intellect Disabil Res. 2015. 59:397–410. doi:10.1111/jir.12139 24761812 | Outcome
45 | McCarley S, López-Ríos M, Burgos Gil R, Using a Community-Based Participatory Mixed Methods Research Approach to Develop, Evaluate, and Refine a Nutrition Intervention to Replace Sugary Drinks with Filtered Tap Water among Predominantly Central-American Immigrant Families with Infants and Toddlers: The Water Up @Home Pilot Evaluation Study. Nutrients. 2021. 13:2942. doi:10.3390/nu13092942 34578820 | Study Design; Single Food Intervention
46 | McEwen MM, Pasvogel A, Murdaugh C, Hepworth J. Effects of a Family-based Diabetes Intervention on Behavioral and Biological Outcomes for Mexican American Adults. Diabetes Educ. 2017. 43:272–285. doi:10.1177/0145721717706031 28447545 | Health Status
47 | Miller ER, Cooper LA, Carson KA, A Dietary Intervention in Urban African Americans: Results of the "Five Plus Nuts and Beans" Randomized Trial. Am J Prev Med. 2016. 50:87–95. doi:10.1016/j.amepre.2015.06.010 26321012 | Health Status
48 | Oppezzo M, Knox M, Skan J, Traditional Heart-Healthy Diet and Medication Adherence in the Norton Sound Region: An 18-Month Telehealth Intervention. Int J Environ Res Public Health. 2022. 19:9885. doi:10.3390/ijerph19169885 36011519 | Health Status
49 | Ortega AN, Albert SL, Chan-Golston AM, Substantial improvements not seen in health behaviors following corner store conversions in two Latino food swamps. BMC Public Health. 2016. 16:389. doi:10.1186/s12889-016-3074-1 27169514 | Intervention not relevant
50 | Otilingam PG, Gatz M, Tello E, Buenos hábitos alimenticios para una buena salud: evaluation of a nutrition education program to improve heart health and brain health in Latinas. J Aging Health. 2015. 27:177–92. doi:10.1177/0898264314549660 25231884 | Outcome
51 | Palmas W, Findley SE, Mejia M, Results of the northern Manhattan diabetes community outreach project: a randomized trial studying a community health worker intervention to improve diabetes care in Hispanic adults. Diabetes Care. 2014. 37:963–9. doi:10.2337/dc13-2142 24496805 | Health Status
52 | Phillips EG, Wells MT, Winston G, Innovative approaches to weight loss in a high-risk population: The small changes and lasting effects (SCALE) trial. Obesity (Silver Spring). 2017. 25:833–841. doi:10.1002/oby.21780 28382755 | Intervention not relevant
53 | Powell-Wiley TM, Banks-Richard K, Williams-King E, Churches as targets for cardiovascular disease prevention: comparison of genes, nutrition, exercise, wellness and spiritual growth (GoodNEWS) and Dallas County populations. J Public Health (Oxf). 2013. 35:99–106. doi:10.1093/pubmed/fds060 22811446 | Study Design
54 | Quintiliani LM, Whiteley JA, Murillo J, Community health worker-delivered weight management intervention among public housing residents: A feasibility study. Prev Med Rep. 2021. 22:101360. doi:10.1016/j.pmedr.2021.101360 33816090 | Intervention not relevant
55 | Ranjit N, Nielsen A, Akhavan N, Outcomes of a Community-Wide Health Intervention in a Low-Income, Primarily Hispanic Community: The Go! Austin/Vamos! Austin (GAVA) Initiative. Health Promot Pract. 2022. 23:185–194. doi:10.1177/1524839920961365 33034208 | Intervention not relevant
56 | Reifsnider E, Shin CN, Todd M, Jeong M, Gallagher M, Moramarco M. How Did They Grow: An Intervention to Reduce Stunted Growth in Low-Income Mexican-American Children. Res Nurs Health. 2016. 39:105–20. doi:10.1002/nur.21714 26915468 | Health Status
57 | Ries AV, Blackman LT, Page RA, Goal setting for health behavior change: evidence from an obesity intervention for rural low-income women. Rural Remote Health. 2014. 14:2682. doi:10.22605/RRH2682.24785265 | Intervention not relevant
58 | Robinson TN, Matheson D, Desai M, Family, community and clinic collaboration to treat overweight and obese children: Stanford GOALS-A randomized controlled trial of a three-year, multi-component, multi-level, multi-setting intervention. Contemp Clin Trials. 2013. 36:421–35. doi:10.1016/j.cct.2013.09.001 24028942 | Study Design
59 | Samaan Z, Schulze KM, Middleton C, South Asian Heart Risk Assessment (SAHARA): Randomized Controlled Trial Design and Pilot Study. JMIR Res Protoc. 2013. 2:e33. doi:10.2196/resprot.2621 23965279 | Intervention not relevant
60 | Sanders OG, Warren TC, Demps-Gaines F, Weaver R, Carson E. Community-based nutrition program aims message at African American females. J Am Diet Assoc. 2002. 102:626–7. doi:10.1016/s0002-8223(02)90139-2 12008982 | Study Design; Publication Status
61 | Schwartz R, Powell L, Keifer M. Family-based risk reduction of obesity and metabolic syndrome: an overview and outcomes of the Idaho Partnership for Hispanic Health. J Health Care Poor Underserved. 2013. 24:129–44. doi:10.1353/hpu.2013.0106 | Study Design
62 | Seguin-Fowler RA, Eldridge GD, Rethorst CD, Improvements and Maintenance of Clinical and Functional Measures Among Rural Women: Strong Hearts, Healthy Communities-2. 0 Cluster Randomized Trial. Circ Cardiovasc Qual Outcomes. 2022. 15:e009333. doi:10.1161/circoutcomes.122.009333 36378768 | Intervention not relevant
63 | Sleet K, Sisson SB, Dev DA, The Impact of Responsive Feeding Practice Training on Teacher Feeding Behaviors in Tribal Early Care and Education: The Food Resource Equity and Sustainability for Health (FRESH) Study. Curr Dev Nutr. 2020. 4:23–32. doi:10.1093/cdn/nzz105 32258996 | Intervention not relevant
64 | Steinberg D, Kay M, Burroughs J, Svetkey LP, Bennett GG. The Effect of a Digital Behavioral Weight Loss Intervention on Adherence to the Dietary Approaches to Stop Hypertension (DASH) Dietary Pattern in Medically Vulnerable Primary Care Patients: Results from a Randomized Controlled Trial. J Acad Nutr Diet. 2019. 119:574–584. doi:10.1016/j.jand.2018.12.011 30905430 | Intervention not relevant
65 | Stern M, Rancourt D, Soca Lozano S, Delivering ADAPT+ to Latino Families Living in Rural Communities: Feasibility and Acceptability of Implementing a Health Promotion Program Including Mindfulness. J Pediatr Psychol. 2023. 48:666–675. doi:10.1093/jpepsy/jsad049 37541829 | Outcome
66 | Stoddard AM, Palombo R, Troped PJ, Sorensen G, Will JC. Cardiovascular disease risk reduction: the Massachusetts WISEWOMAN project. J Womens Health (Larchmt). 2004. 13:539–46. doi:10.1089/1540999041281106 15257845 | Intervention not relevant
67 | Sullivan J, Carter JP. A nutrition-physical fitness intervention program for low-income black parents. J Natl Med Assoc. 1985. 77:39–43.3968714 | Study Design; Intervention not relevant
68 | Thomas VG, Gaston MH, Porter GK, Anderson A. Prime Time Sister Circles(®)II: Evaluating a Culturally Relevant Intervention to Decrease Psychological and Physical Risk Factors for Chronic Disease in Mid-Life African American Women. J Natl Med Assoc. 2016. 108:6–18. doi:10.1016/j.jnma.2015.12.001 26928483 | Outcome
69 | Thompson B, Coronado G, Chen L, Islas I. Celebremos la salud! a community randomized trial of cancer prevention (United States). Cancer Causes Control. 2006. 17:733–46. doi:10.1007/s10552-006-0006-x 16633921 | Study Design
70 | Thompson DA, Haemer MA, Krebs NF, A WIC-Based Behavior Change Intervention for Postpartum Women With Overweight and Obesity: A Pilot Feasibility Randomized Trial. Health Promot Pract. 2023. 25:677–688. doi:10.1177/15248399231173704 37226873 | Intervention not relevant
71 | Wagner EH, Wickizer TM, Cheadle A, The Kaiser Family Foundation Community Health Promotion Grants Program: findings from an outcome evaluation. Health Serv Res. 2000. 35:561–89.10966086 | Study Design; Intervention not relevant
72 | Wagner J, Bermúdez-Millán A, Buckley T, Self-reported outcomes of a randomized trial comparing three community health worker interventions for diabetes prevention among Cambodian Americans with depression. Patient Educ Couns. 2022. 105:3501–3508. doi:10.1016/j.pec.2022.09.011 36307274 | Health Status
73 | Walters KL, LaMarr J, Levy RL, Project həli?dx(w)/Healthy Hearts Across Generations: development and evaluation design of a tribally based cardiovascular disease prevention intervention for American Indian families. J Prim Prev. 2012. 33:197–207. doi:10.1007/s10935–012-0274-z 22965622 | Study Design
74 | Wang ML, Otis M, Rosal MC, Griecci CF, Lemon SC. Reducing sugary drink intake through youth empowerment: results from a pilot-site randomized study. Int J Behav Nutr Phys Act. 2019. 16:58. doi:10.1186/s12966-019-0819-0 31362753 | Intervention not relevant
75 | Wong WW, Ortiz CL, Stuff JE, A Community-based Healthy Living Promotion Program Improved Self-esteem Among Minority Children. J Pediatr Gastroenterol Nutr. 2016. 63:106–12. doi:10.1097/mpg.0000000000001088 27336592 | Intervention not relevant
76 | Zoellner J, Hill JL, Grier K, Randomized controlled trial targeting obesity-related behaviors: Better Together Healthy Caswell County. Prev Chronic Dis. 2013. 10:E96. doi:10.5888/pcd10.120296 23764345 | Intervention not relevant
77 | Zoellner JM, Connell CC, Madson MB, H.U.B city steps: methods and early findings from a community-based participatory research trial to reduce blood pressure among African Americans. Int J Behav Nutr Phys Act. 2011. 8:59. doi:10.1186/1479-5868-8-59 21663652 | Study Design
78 | Zou, P, Dennis, CL, Lee, R, Parry, M. Dietary Approach to Stop Hypertension with Sodium Reduction for Chinese Canadians (DASHNa-CC): A Pilot Randomized Controlled Trial. J Nutr Health Aging. 2017. 21:1225–1232. doi:10.1007/s12603-016-0861-4 29188883 | Health Status