# Appendix 2 Literature search strategy

NESR evidence scans use streamlined search methods to obtain an estimate of the volume and characteristics of evidence available in an efficient way.^*^ In this evidence scan, several steps were taken to streamline the search:

- Search limited to one database (PubMed);
- Racial groups were named in the search string, but specific ethnic groups were not; and,
- Included results needed to include both a term related to culture or community and a minoritized people group.

* USDA Nutrition Evidence Systematic Review Branch. Chapter 9: Evidence Scans. In: USDA Nutrition Evidence Systematic Review: Methodology Manual. February 2023. U.S. Department of Agriculture, Food and Nutrition Service, Center for Nutrition Policy and Promotion, Nutrition Evidence Systematic Review. Available at: https://nesr.usda.gov/methodology-overview

These steps mean that the search is not inclusive of all possible results, but rather an overview of the distribution and characteristics of the body of evidence.

## Database: PubMed

Provider: U.S. National Library of Medicine

Date(s) Searched: January 30, 2024

Dates Covered: January 1, 1980 – September 30, 2023

Table A 2 Search for PubMed

Search # | Concept | String
#1 | Culturally tailored interventions | ((Cultur*[tiab] OR communit*[tiab]) AND (“Health Disparate, Minority and Vulnerable Populations”[Mesh:NoExp] OR “Racial Groups”[MeSH] OR “Asian People”[MeSH] OR “African People”[MeSH] OR “Caribbean People”[MeSH] OR “Central American People”[MeSH] OR “Middle Eastern and North Africans”[MeSH] OR “Oceanians”[MeSH] OR “South American People”[MeSH] OR .“Ethnicity”[MESH] OR Race[tiab] OR racial*[tiab] OR ethnic*[tiab] OR African American*[tiab] OR Asian*[tiab] OR Pacific Islander*[tiab] OR black[tiab] OR blacks[tiab] OR Hispanic*[tiab] OR Latina*[tiab] OR Latino*[tiab] OR Latinx[tiab] OR Caribbean[tiab] OR AfroCaribbean[tiab] OR AfroLatin*[tiab]OR Arab[tiab] OR multiethnic[tiab] OR multiracial[tiab] OR sociodemographic*[tiab] OR socio demographic*[tiab] OR underserved[tiab] OR under-served[tiab] OR underrepresented[tiab] OR under-represented[tiab] OR American Indian*[tiab] OR Native American*[tiab] OR Alaska Native*[tiab] OR Native Alaskan*[tiab] OR Hawaiian Native*[tiab] OR Native Hawaiian*[tiab] OR “Health Services, Indigenous”[Mesh] OR Nunavut[tiab] OR Aborigin*[TIAB] OR indigene*[tiab] OR indigenous*[tiab] OR tribe*[tiab] OR tribal*[tiab] OR autochtone*[tiab] OR eskimo*[tiab] OR Esquimau*[tiab] OR “first nation*”[tiab] OR “first people*”[tiab] OR “indian band”[tiab:~1] OR “band council”[tiab:~1] OR Inuit[tiab] OR Innuit*[TIAB] OR Inuk*[tiab] OR Inupiat*[tiab] OR Pima[tiab] OR metis[tiab] OR “Mixed-blood*”[tiab] OR “Original people*”[tiab] OR Amerind*[tiab] OR ((indian[tiab] or indians[tiab]) AND (Canad*[tiab] OR America*[tiab] OR urban[tiab] OR reservation*[tiab])))) OR “food sovereignty”[tiab] OR “food ways”[tiab] OR “traditional food”[tiab:~1] OR “traditional foods”[tiab:~1] OR “country food*”[tiab]
#2 | Dietary intake | (“dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “diet variety”[tiab] OR “dietary variety”[tiab] OR “varied diet”[tiab] OR “dietary guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary intake*”[tiab] OR “eating style*”[tiab] OR “Diet, Mediterranean”[Mesh] OR “Mediterranean Diet*”[tiab] OR “Dietary Approaches To Stop Hypertension”[Mesh] OR “Dietary Approaches To Stop Hypertension Diet*”[tiab] OR “DASH diet*”[tiab] OR “Diet, Gluten-Free”[Mesh] OR “Gluten Free diet*”[tiab] OR “prudent diet*”[tiab] OR “Diet, Paleolithic”[Mesh] OR “Paleolithic Diet*”[tiab] OR “Diet, Vegetarian”[Mesh] OR “vegetarian diet*”[tiab] OR “vegan diet*”[tiab] OR “Diet, Healthy”[Mesh] OR “healthy diet*”[tiab] OR “plant based diet*”[tiab] OR “Diet, Western”[Mesh] OR “western diet*”[tiab] OR “Nordic Diet*”[tiab] OR “Okinawan diet*”[tiab] OR “Diet, Fat-Restricted”[Mesh] OR “Diet, High-Fat”[Mesh] OR “high‐fat diet*”[tiab] OR “low fat diet*”[tiab] OR “Diet, Sodium-Restricted”[Mesh] OR “low-sodium diet*”[tiab] OR “low salt diet*”[tiab] OR ((“Guideline Adherence”[Mesh] OR “guideline adherence*”[tiab])AND (diet[tiab] OR dietary[tiab] OR food[tiab] OR beverage*[tiab] OR nutrition*[tiab])) OR “diet score*”[tiab] OR “diet quality score*”[tiab] OR “diet quality index*”[tiab] OR “diet quality indices”[tiab] OR kidmed[tiab] OR “diet index*”[tiab] OR “diet indices”[tiab] OR “dietary index*”[tiab] OR “dietary indices”[tiab] OR “food score*”[tiab] OR MedDietScore[tiab] OR “healthy eating index*”[tiab] OR “healthy eating indices”[tiab])
#3 | Alignment with dietary guidelines | “Guideline Adherence”[Mesh] OR HEI[tiab] OR “healthy eating index”[tiab] OR “dietary guideline*”[tiab] OR “nutrition guideline*”[tiab] OR “nutritional guideline*”[tiab] OR “dietary recommendation*”[tiab] OR “dietary consumption”[tiab] OR “diet score*”[tiab] OR “diet index*”[tiab] OR “diet indices”[tiab] OR “dietary index*”[tiab] OR “dietary indices”[tiab] OR “food score*”[tiab] OR “dietary pattern*”[tiab] OR “diet pattern*”[tiab] OR “eating pattern*”[tiab] OR “food pattern*”[tiab] OR “diet quality”[tiab] OR “dietary quality”[tiab] OR “Healthy diet”[tiab] OR kidmed[tiab] OR MedDietScore[tiab] OR “Fruit”[MeSH] OR “Vegetables”[MeSH] OR Fruit*[tiab] OR vegetable*[tiab] OR citrus*[tiab] OR berry[tiab] OR berries[tiab] OR “leafy green”[tiab:~3] OR “leafy greens”[tiab:~3] OR “Edible Grain”[MeSH] OR “whole grain*”[tiab] OR wholegrain*[tiab] OR “whole meal”[tiab] OR wholemeal[tiab] OR “whole wheat”[tiab] OR wholewheat[tiab] OR “Sugar Sweetened Beverages”[MeSH] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR ((“Dietary Sugars”[Mesh] OR sugar*[tiab]) AND (“Beverages”[Mesh:NoExp] OR beverage*[tiab] OR drink*[tiab] OR “Carbonated Beverages”[Mesh] OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR “Coffee”[Mesh] OR coffee*[tiab] OR “Tea”[Mesh] OR tea[tiab] OR teas[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR liquid[tiab] OR liquids[tiab]))
#4 | Energy Intake | “Energy Intake”[MeSH] OR “energy intake”[tiab] OR “calorie intake”[tiab] OR “caloric intake”[tiab] OR “total energy”[tiab] OR “total calorie*”[tiab] OR “total caloric*”[tiab] OR “energy consum*”[tiab] OR “calorie consum*”[tiab] OR “caloric consum*”[tiab]
#5 | Dietary topics | Food*[tiab] OR diet*[tiab] OR eating[tiab] OR nutrition*[tiab]
#6 | Psychosocial factors | “Psychosocial factor*”[tiab] OR “psycho social factor*” OR norm[tiab] OR norms[tiab] OR expectation*[tiab] OR attitude*[tiab] OR value*[tiab] OR “self efficacy”[tiab] OR “self esteem”[tiab] OR confidence[tiab]
#7 | Cardiovascular disease | “Cardiovascular Diseases”[Mesh:NoExp] OR “cardiovascular disease*”[tiab] OR “coronary artery disease”[tiab] OR “heart disease*”[tiab] OR “Heart Failure”[Mesh] OR “heart failure”[tiab] OR “myocardial infarction*”[tiab] OR “Myocardial Ischemia”[Mesh] OR “myocardial ischemia*”[tiab] OR “Stroke”[Mesh] OR “stroke*”[tiab] OR “angina”[tiab] OR “heart attack*”[tiab] OR “Venous Thrombosis”[Mesh] OR “venous thrombosis”[tiab] OR “hypertension”[tiab] OR “Blood Pressure”[Mesh:NoExp] OR “high blood pressure”[tiab] OR “Lipids/blood”[Mesh] OR “Cholesterol, HDL”[Mesh] OR “HDL cholesterol”[tiab] OR “Cholesterol, LDL”[Mesh] OR “LDL cholesterol”[tiab] OR “total cholesterol”[tiab] OR “blood cholesterol”[tiab] OR “Triglycerides”[Mesh] OR “triglycerides”[tiab] OR “Hypertension”[Mesh:NoExp] OR hypertensi*[tiab] OR Lipoprotein[tiab] OR “lipid profile*”[tiab] OR “Hypertension, Pregnancy-Induced”[Mesh] OR “Pre-Eclamp*”[tiab] OR preeclamp*[tiab] OR Eclamp*[tiab] OR (Cardiovascular[tiab] AND risk*[tiab])
#8 | Type 2 diabetes | “Diabetes Mellitus”[Mesh:NoExp] OR “Diabetes Mellitus, Type 2”[Mesh] OR “type 2 diabet*”[tiab] OR “T2D”[tiab] OR “adult onset diabetes”[tiab] OR “Prediabetic State”[Mesh] OR “prediabet*”[tiab] OR “pre diabet*”[tiab] OR “Insulin Resistance”[Mesh] OR “insulin resistance”[tiab] OR “insulin resistant”[tiab] OR “glucose intolerance”[tiab] OR “glucose intolerant”[tiab] OR “glucose tolerance”[tiab] OR “glucose tolerant”[tiab] OR “Glycated Hemoglobin”[Mesh] OR “hemoglobin A1c”[tiab] OR hba1c[tiab] OR “hba 1c”[tiab] OR “haemoglobin A1c”[tiab] OR “Hyperglycemia”[Mesh] OR “hyperglycemia”[tiab] OR hyperglycaemia[tiab] OR “Hypoglycemia”[Mesh] OR “hypoglycemia”[tiab] OR hypoglycaemia[tiab] OR ((impaired[tiab] OR glucose[tiab]) AND fasting[tiab]) OR “blood glucose”[MeSH] OR “blood glucose”[tiab] OR “plasma glucose”[tiab] OR “serum glucose”[tiab] OR “glycemi*”[tiab] OR glycaemi*[tiab] OR “blood sugar”[tiab] OR dysglycemi*[tiab] OR dysglycaemi*[tiab] OR hyperinsulinism[MeSH] OR hyperinsulin*[tiab] OR “Diabetes, Gestational”[Mesh] OR (gestation*[tiab] AND diabet*[tiab]) OR (“Maternal Nutritional Physiological Phenomena”[Mesh] AND diabet*[tiab])
#9 | Growth, body composition, and risk of obesity | “Adipose Tissue”[Mesh] OR “Body Composition”[Mesh] OR “Body Weights and Measures”[MeSH:NoExp] OR “Body Fat Distribution”[Mesh] OR “Body Mass Index”[Mesh] OR “Body Size”[Mesh] OR “Skinfold Thickness”[Mesh] OR “Waist-Hip Ratio”[Mesh] OR “Overnutrition”[Mesh] OR “Growth”[Mesh:NoExp] OR anthropometr*[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR lean mass[tiab] OR obese[tiab] OR obesity[tiab] OR underweight[tiab] OR overweight[tiab] OR weight status[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR calf circumference[tiab] OR neck circumference[tiab] OR thigh circumference[tiab] OR waist circumference[tiab] OR waist to hip ratio[tiab] OR waist hip ratio[tiab] OR body mass index[tiab] OR BMI[tiab] OR adipos*[tiab] OR body weight[tiab] OR body height[tiab] OR body size[tiab] OR body composition[tiab] OR overnutrition[tiab] OR wasting[tiab] OR healthy weight[tiab] OR skin fold[tiab] OR skin folds[tiab] OR skinfold[tiab] OR skinfolds[tiab] OR “Weight Reduction Programs”[Mesh] OR “Body-Weight Trajectory”[Mesh] OR “Weight Gain”[MeSH] OR “Weight Loss”[MeSH:NoExp] OR “Diet, Reducing”[Mesh] OR weight gain*[tiab] OR diet reduc*[tiab] OR weight cycling[tiab] OR weight decreas*[tiab] OR weight watch*[tiab] OR weight control*[tiab] OR weight retention[tiab] OR weight management[tiab] OR “maintain weight”[tiab:~4] OR “maintains weight”[tiab:~4] OR “maintaining weight”[tiab:~4] OR “maintained weight”[tiab:~4] OR “weight maintenance”[tiab:~4] OR “reduce weight”[tiab:~4] OR “reduces weight”[tiab:~4] OR “reducing weight”[tiab:~4] OR “reduced weight”[tiab:~4] OR “weight reduction”[tiab:~4] OR “lose weight”[tiab:~4] OR “loses weight”[tiab:~4] OR “losing weight”[tiab:~4] OR “lost weight”[tiab:~4] OR “weight loss”[tiab:~4] OR “change weight”[tiab:~4] OR “changes weight”[tiab:~4] OR “changing weight”[tiab:~4] OR “changed weight”[tiab:~4]; OR “Growth Charts”[Mesh] OR growth chart*[tiab]OR stunting[tiab] OR stunted[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR length for age[tiab] OR weight for length[tiab] OR failure to thrive[tiab]
#10 | | #1 AND ((#2 OR #3 OR #4) OR (#5 AND (#6 OR #7 OR #8 OR #9)))
#11 | Limits | #10 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND "Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR commentary[tiab] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR protocol[ti] OR protocols[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti] OR “retracted publication”[ti] OR “Congress”[Publication Type] OR “Consensus Development Conference”[Publication Type] OR “conference abstract*”[tiab] OR “conference proceeding*”[tiab] OR “conference paper*”[tiab] OR “practice guideline”[ptyp] OR “practice guideline”[ti]); Filters applied: English, from 2000/1/1 – 2023/09/30.