# Appendix 1 Abbreviations

Table A 1 List of abbreviations
Abbreviation: Full name
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NRCT: Non-randomized controlled trial
RCT: Randomized controlled trial
USDA: United States Department of Agriculture