# List of abbreviations

Abbreviation: Full name
HbA1C: Hemoglobin A1C
HOMA-IR: Homeostasis Model of Insulin Resistance
NESR: Nutrition Evidence Systematic Review
PROBIT: Promotion of Breastfeeding Intervention Trial
TEC: Technical Expert Collaborative