# List of abbreviations

Abbreviation: Full name
CVD: cardiovascular disease
DBP: diastolic blood pressure
HDL: high-density lipoprotein
LDL: low-density lipoprotein
NESR: Nutrition Evidence Systematic Review
PROBIT: Promotion of Breastfeeding Intervention Trial
SBP: systolic blood pressure
TEC: Technical Expert Collaborative