# List of abbreviations

Abbreviation: Full name
IBD: Inflammatory Bowel Disease
NESR: Nutrition Evidence Systematic Review
TEC: Technical Expert Collaborative