# List of abbreviations

Abbreviation: Full name
BMI: Body Mass Index
DAISY: Diabetes Autoimmunity Study in the Young
DiMe: Childhood Diabetes in Finland
EURODIAB ACE: European Diabetes: Aetiology of Childhood diabetes on an Epidemiological basis
HbA1C: Hemoglobin A1C
HOMA-IR: Homeostasis Model of Insulin Resistance
MIDIA: Environmental Triggers of Type 1 Diabetes
NESR: Nutrition Evidence Systematic Review
PROBIT: Promotion of Breastfeeding Intervention Trial
SOLAR: Study of Latino Adolescents at Risk for diabetes
TEC: Technical Expert Collaborative