# List of abbreviations

Abbreviation: Full name
DBH: Dampness in Buildings and Health
IgE: Immunoglobulin E
ISAAC: International Study of Asthma and Allergy in Childhood
NESR: Nutrition Evidence Systematic Review
PROBIT: Promotion of Breastfeeding Intervention Trial
SCORAD: SCORing Atopic Dermatitis
TEC: Technical Expert Collaborative