# ACKNOWLEDGEMENTS

Flavor exposure & Feeding practices Technical Expert Collaborative (TEC):

- Sara Benjamin-Neelon, PhD, MPH, RD, Johns Hopkins University
- Leann Birch, PhD, University of Georgia
- Maureen Black, PhD, University of Maryland School of Medicine and RTI International
- Ronette Briefel, DrPH, MPH, RD, Mathematica Policy Institute
- John Cook, PhD, MAEd, Boston Medical Center
- Myles Faith, PhD, University at Buffalo
- Julie Mennella, PhD, Monell Chemical Senses Center

Nutrition Evidence Systematic Review (NESR) Team:

- Maureen Spill^i^, PhD, Panum Group, Lead analyst
- Emily Gower^i^, MS, Panum Group, Analyst (from 11/2016)
- Kirsten Johns^i^, MS, Panum Group, Analyst (until 01/2017)
- Myra Shapiro^i^, PhD, Panum Group, Analyst (from 01/2017)
- Joanne Spahn, MS, USDA, Analyst
- Yat Ping Wong, MLS, MPH, USDA, Librarian
- Nancy Terry, MLS, NIH, Librarian

Project Leads:

- Kellie Casavale, PhD, RD, HHS
- Joanne Spahn, MS, RD, FADA, USDA
- Eve Essery Stoody, PhD, USDA

Federal Expert Group (FEG)-Technical Expert Collaborative (TEC) Liaisons:

- Andrea Farmer, MS, RD, LD, USDA (until 05/2016)
- Heather Hamner, PhD, MS, MPH, CDC (from 05/2016)
- Cria Perrine, PhD, CDC (from 10/2016)

All TEC and NESR team members, Project leads, and FEG-TEC liaisons participated in establishing the research questions, analytic framework, and study inclusion and exclusion criteria. MKS, KJ, EHC, MJS, and JMS wrote the manuscript, screened, extracted data and assessed risk of bias independently. YPW designed and conducted the literature search. SBN, LB, MB, RB, JTC, MSF, and JAM designed the protocol and provided substantive input to evidence synthesis, conclusion statement. KOC, JMS, and EES provided oversight of the project. All authors critically reviewed the manuscript and approved the final version. The authors declare no conflicts of interest.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.