# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
BMIZ: Body mass index z-score
HHS: United States Department of Health and Human Services
NEL: Nutrition Evidence Library
NEL BAT: NEL Bias Assessment Tool
RCT: Randomized controlled trial
RoB: Risk of bias
SR: Systematic Review
TEC: Technical Expert Collaborative
USDA: United States Department of Agriculture
WAZ: Weight-for-age z-score
WLZ: Weight-for-length z-score