# ACKNOWLEDGEMENTS

Technical Expert Collaborative (TEC) members:

- Nancy F. Butte, PhD, RD, USDA/ARS Children’s Nutrition Research Center, Baylor College of Medicine, Department of Pediatrics, Emeritus
- Kathryn G. Dewey, PhD, University of California, Davis, Department of Nutrition
- David M. Fleischer, MD, Children’s Hospital Colorado, University of Colorado School of Medicine, Department of Pediatrics, Section of Allergy and Immunology
- Mary Kay Fox, Med, Mathematic Policy Research
- Frank R. Greer, MD, University of Wisconsin School of Medicine and Public Health, Department of Pediatrics, Emeritus
- Nancy F. Krebs, MD, MS, University of Colorado School of Medicine, Department of Pediatrics
- Kelley S. Scanlon, PhD, RD, USDA Food and Nutrition Service; formerly of the Centers for Disease Control and Prevention, Division of Nutrition, Physical Activity, and Obesity

Nutrition Evidence Systematic Review (NESR) team:

- Laural K. English^i^, PhD, Panum Group, Lead Analyst (11/2016-project completion)
- Julie E. Obbagy, PhD, RD, USDA, Analyst (05/2016-project completion)
- Yat Ping Wong, MLS, MPH, USDA, Librarian
- Tricia Psota, PhD, USDA, Analyst (07/2015-06/2016)
- Perrine Naudad^i^, PhD, Panum Group, Analyst (07/2015-05/2016)
- Kirsten Johns^i^, MS, Panum Group, Analyst (07/2015-05/2016)
- Nancy Terry, MLS, NIH, Librarian

Project Leads:

- Eve Essery Stoody, PhD, USDA
- Joanne M Spahn, MS, RD, FADA, USDA
- Kellie O Casavale, PhD, RD, HHS

Federal Expert Group (FEG)-Technical Expert Collaborative (TEC) Liaisons:

- Kelley Scanlon, PhD, RD, USDA Food and Nutrition Service; formerly of the Centers for Disease Control and Prevention, Division of Nutrition, Physical Activity, and Obesity

All TEC and NESR team members, Project leads, and FEG-TEC liaisons participated in establishing the research questions, analytic framework, and study inclusion and exclusion criteria. LKE, JEO, YPW, TLP, PN, KJ, and NT developed and conducted the literature search, screened search results, and identified studies for inclusion. LKE and JEO extracted data and assessed risk of bias for included studies. NFC, KGD, DMF, MKF, FRG, NFK, and KSS reviewed and provided substantive feedback on all systematic review materials, including the synthesis of the body of evidence, conclusion statement, and grade of the strength of the evidence. LKE prepared this report and EES provided oversight. All authors critically reviewed and approved the final report. The authors declare no conflicts of interest.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.