# List of abbreviations

Abbreviation: Full description
BF: Breast fed
BSID: Bayley Scale of Infant Development
CFB: Complementary Food and Beverage
CFUI: Complementary feeding utility index
EBF: Exclusively breast-fed
FEG: Federal Expert Group
HHS: Department of Health and Human Services
IQ: Intelligence quotient
MDI: Mental development index
NEL: Nutrition Evidence Library
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
PDI: Psychomotor development index
P/B-24: Pregnancy and Birth to 24 Months Project
TEC: Technical Expert Collaborative
U.K.: United Kingdom
U.S.: United States
USDA: United States Department of Agriculture
WISC: Wechsler Intelligence Scale for Children