# ACKNOWLEDGEMENTS

Beverage and Added Sugars Subcommittee:

- Elizabeth Mayer-Davis, PhD, RD, University of North Carolina at Chapel Hill, Subcommittee Chair
- Heather Leidy, PhD, University of Texas at Austin
- Richard Mattes, PhD, MPH, RD, Purdue University
- Timothy Naimi, MD, MPH, Boston University
- Rachel Novotny, PhD, RDN, LD, University of Hawaii
- Barbara Schneeman, PhD, University of California, Davis, Chair of the 2020 Dietary Guidelines Advisory Committee

Nutrition Evidence Systematic Review (NESR) Team:

- Brittany James Kingshipp, PhD, Analyst, Panum Group^i^
- Maureen Spill, PhD, Analyst, Panum Group^i^
- Natasha Chong Cole, PhD, MPH, RD, Analyst, Panum Group^i^
- Charlotte Bahnfleth, PhD, Analyst, Panum Group^i^
- Gisela Butera, MLIS, MEd, Systematic Review Librarian, Panum Group^i^
- Nancy Terry, MS, MLS, Biomedical Librarian, National Institutes of Health Library, U.S. Department of Health and Human Services (HHS)
- Julie Obbagy, PhD, RD, Project lead, Nutrition Guidance and Analysis Division (NGAD), Center for Nutrition Policy and Promotion (CNPP), Food and Nutrition Service (FNS), U.S. Department of Agriculture (USDA)

Federal Liaisons:

- Jennifer Seymour, PhD, Division of Nutrition, Physical Activity, and Obesity, Centers for Disease Control and Prevention, U.S. Department of Health and Human Services (HHS)
- Julia Quam, MSPH, RDN, Division of Prevention Science (DPS), Office of Disease Prevention and Health Promotion (ODPHP), HHS
- Clarissa (Claire) Brown, MS, MPH, RDN, NGAD, CNPP, FNS, USDA
- Meghan Adler, MS, RDN, NGAD, CNPP, FNS, USDA

Project Leadership:

- Eve Stoody, PhD, Designated Federal Officer and Director, NGAD, CNPP, FNS USDA
- Janet de Jesus, MS, RD, Nutrition Advisor, DPS, ODPHP, Office of the Assistant Secretary for Health (OASH), HHS
- Richard (Rick) Olson, MD, MPH, Director, DPS, ODPHP, OASH, HHS

USDA and HHS implemented a process to identify topics and scientific questions to be examined by the 2020 Dietary Guidelines Advisory Committee. The Committee conducted its review of evidence in subcommittees for discussion by the full Committee during its public meetings. The role of the Committee members involved establishing all aspects of the protocol, which presented the plan for how they would examine the scientific evidence, including the inclusion and exclusion criteria; reviewing all studies that met the criteria they set; deliberating on the body of evidence for each question; and writing and grading the conclusion statements to be included in the scientific report the 2020 Committee submitted to USDA and HHS. The NESR team with assistance from Federal Liaisons and Project Leadership, supported the Committee by facilitating, executing, and documenting the work necessary to ensure the reviews were completed in accordance with NESR methodology. More information about the 2020 Dietary Guidelines Advisory Committee, including the process used to identify topics and questions, can be found at www.DietaryGuidelines.gov. More information about NESR can be found at NESR.usda.gov.

The Committee and NESR staff thank USDA’s Agricultural Research Service for coordinating the peer review of this systematic review, and the Federal scientist peer reviewers for their time and expertise.

i Under contract with the Food and Nutrition Service, United States Department of Agriculture.