# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
FNS: Food and Nutrition Service
HDI: Human development index
HHS: Health and Human Services
LNCSB: Low or no calorie sweetened beverage
NESR: Nutrition Evidence Systematic Review
NRCT: Non-randomized controlled trials
OASH: Office of the Assistant Secretary for Health
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
PICO: Population, intervention/exposure, comparators, and outcomes
PCS: Prospective cohort study
RCT: Randomized controlled trials
SSB: Sugar-sweetened beverage
UK: United Kingdom
US: United States
USDA: U.S. Departments of Agriculture