# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^lxvi^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 10. Beverages.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on beverage consumption and growth, size, body composition, and risk of overweight and obesity. For this systematic review, the target populations considered were children through older adults, ages 2y+. The interventions or exposures considered were the type and amount of beverage consumption and the comparators were different amount of the same beverage (including no consumption and versions diluted with water), beverage vs. solid, beverage vs. water, sugar-sweetened beverages vs. no- or low-calorie sweetened beverages, and dairy milk with different amounts of fat. The outcomes considered were weight, weight-for-age, height, length/stature-for-age, BMI, BMI z-score, weight-for-length, body circumferences: head, arm, waist, thigh, neck, body composition and distribution (e.g., % fat mass, % fat free mass), and incidence and prevalence of: underweight, failure to thrive, stunting, wasting, healthy weight, overweight, and obesity. The key confounders were age, sex, race/ethnicity, socioeconomic status, anthropometry at baseline, and smoking. Other factors to be considered were total energy intake, timing, temporal use, sugar, protein, fiber, energy density, alcohol, medications, supplements, and study duration.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table (Table 32) provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 32 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials (including quasi experimental and controlled before-and-after studies); - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies; - Mendelian randomization studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Obesity treatment studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | Type and amount of beverage consumption of the following beverage types:; - Milk (dairy milk and milk substitutes, including flavored milk); - 100% Juice; - Low- or no-calorie sweetened beverages (LNCSB); - Sugar-sweetened beverages (SSB) | - Other beverage types, including: Coffee, tea, water, and nutritional beverages (e.g., protein shakes, smoothies); - Studies focusing on specific nutrients added to beverages instead of a beverage as a whole (i.e., studies where beverages are the delivery mechanism for a nutrient); - Beverages that are not commercially available (e.g., experimentally manipulated beverages); - Supplements; - Alcohol; - Soups
Comparator | - Different amount of the same beverage (including no consumption and versions diluted with water); - Beverage vs. solid; - Beverage vs. water; - Sugar-sweetened beverages vs. low- or no-calorie sweetened beverages; - Dairy milk with different amounts of fat | - No comparator; - Studies comparing different types of beverages (with the exception of studies comparing a beverage to plain water, dairy milk with different amounts of fat, and sugar-sweetened beverages to low- or no-calorie sweetened beverages)
Outcomes | - Weight, weight-for-age; - Height, length/stature-for-age; - BMI, BMI z-score, weight-for-length; - Body circumferences: head, arm, waist, thigh, neck; - Body composition and distribution (e.g., % fat mass, % fat free mass); - Incidence and prevalence of:; ○ Underweight, failure to thrive, stunting, wasting; ○ Healthy weight; ○ Overweight; ○ Obesity
Date of publication | - For Milk, Juice, LNCSB: January 2000 – June 2019; - For SSB: January 2012 – June 2019^lxvii^ | - For Milk, Juice, LNCSB: Articles published prior to 2000; - For SSB: articles published prior to 2012
Publication status | - Articles published in peer-reviewed journals | - Articles not published in peerreviewed journals, including unpublished data, manuscripts, reports, preprints, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^lxviii^ | - Studies conducted in Very High or High Human Development Countries | - Studies conducted in Medium or lower Human Development Countries
Study participants | - Human subjects; - Males; - Females (including pregnant and lactating women) | - Animal subjects; - Hospitalized samples
Age of study participants | - Age at intervention or exposure:; - Child (2-5 years); - Child (6-12 years); - Adolescents (13-18 years); - Adults (19 and older); - Older adults (65+ years); - Age at outcome:; - Child (2-5 years); - Child (6-12 years); - Adolescents (13-18 years); - Adults (19 and older); - Older adults (65+ years) | - Age at intervention or exposure: <2y; - Age at outcome: <2y
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants who are classified as underweight, stunted, wasted, or obese | - Studies that exclusively enroll participants diagnosed with a disease, or hospitalized with an illness or injury; - Studies that exclusively enroll participants classified as obese (i.e., studies that aim to treat participants who have already been classified as obese)

### Electronic databases and search terms

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the update to the existing systematic review.

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: June 20, 2019
- Date range searched: January 1, 2000-June 20, 2019
- Search Terms:
  - #1 - “Beverages”[Mesh:NoExp] OR beverage[tiab] OR beverages[tiab] OR sports drink* OR protein drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR nutritional drink* OR smoothie*[tiab] OR protein shake* OR meal replacement*[tiab] OR carbonated drink*[tiab] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR caffeinated drink*[tiab] OR “Drinking Water”[Mesh] OR drinking water[tiab] OR bottled water[tiab] OR “Carbonated Beverages”[Mesh] OR carbonated water[tiab] OR sparkling water[tiab] OR flavored water[tiab] OR flavoured water[tiab] OR flavoured drink[tiab] OR flavored drink* OR “Energy Drinks”[Mesh] OR energy drink*[tiab] OR sugar sweetened drink* OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR fruit drink* OR fizzy drink* OR “Coffee”[Mesh] OR coffee[tiab] OR “Tea”[Mesh] OR tea[tiab] OR “Milk”[Mesh:NoExp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR “Buttermilk”[Mesh] OR buttermilk[tiab] OR “Whey”[Mesh] OR whey[tiab] OR liquid[tiab] OR liquids[tiab]
  - #2 - “Body Composition”[Mesh] OR body composition[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR healthy weight[tiab] OR underweight[tiab] OR wasting[tiab] OR failure to thrive[tiab] OR “Waist Circumference”[Mesh] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR “Body Height”[Mesh:NoExp] OR body height[tiab] OR stunting[tiab] OR stunted[tiab] OR “Overweight”[Mesh] OR overweight[tiab] OR obesity[tiab] OR obese[tiab] OR “Body Mass Index”[Mesh] OR body mass index[tiab] OR BMI[tiab] OR body fat[tiab]
  - #3 - (#1 AND #2) NOT (("Animals”[Mesh] NOT ("Animals”[Mesh] AND “Humans”[Mesh])))) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2019/06/20; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: June 20, 2019
- Date range searched: January 1, 2000-June 20, 2019
- Search Terms:
  - #1 - [mh ^Beverages] OR [mh “Drinking Water”] OR [mh “Carbonated Beverage”] OR [mh “Energy Drink”] OR [mh “Fruit and Vegetable Juice”] OR [mh Coffee] OR [mh ^Milk]
  - #2 - (beverage OR beverages OR “sports drink” OR “protein drink” OR “fortified drink” OR “sweetened drink” OR “sweet drink” OR “sugary drink” OR “dairy drink” OR “chocolate drink” OR “nutritional drink” OR smoothie* OR “protein shake” OR “meal replacement” OR “carbonated drink” OR “soft drink” OR soda OR sodas OR “caffeinated drink” OR “drinking water” OR “bottled water” OR “carbonated water” OR “sparkling water” OR “flavored water” OR “flavoured water” OR “flavoured drink” OR “flavored drink*” OR “energy drink” OR “sugar sweetened drink” OR juice OR juices OR “fruit drink” OR “fizzy drink” OR coffee OR tea OR milk OR soymilk OR buttermilk OR whey OR liquid OR liquids):ti,ab,kw”
  - #3 - #1 OR #2”
  - #4 - [mh “Body Composition”] OR [mh “Waist Circumference”] OR [mh ^"Body Height”] OR [mh “Overweight”] OR [mh “Body Mass Index”]
  - #5 - (“body composition” OR “fat mass” OR “fat free mass” OR “healthy weight” OR underweight OR wasting OR “failure to thrive” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR “body height” OR stunting OR stunted OR overweight OR obesity OR obese OR “body mass index” OR BMI OR “body fat”):ti,ab,kw”
  - #6- #4 OR #5
  - #7 - #3 AND #6 with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: June 20, 2019
- Date range searched: January 1, 2000-June 20, 2019
- Search Terms:
  - #1- ‘beverage’/mj OR ‘drinking water’/mj OR ‘carbonated beverage’/de OR ‘energy drink’/de OR ‘fruit and vegetable juice’/exp/mj OR ‘coffee’/exp/mj OR ‘milk’/mj OR ‘soybean milk’/de OR ‘buttermilk’/de OR ‘whey’/de
  - #2 - beverage OR beverages OR ‘sports drink*’ OR ‘protein drink*’ OR ‘fortified drink*’ OR ‘sweetened drink*’ OR ‘sweet drink*’ OR ‘sugary drink*’ OR ‘dairy drink*’ OR ‘chocolate drink*’ OR ‘nutritional drink*’ OR smoothie* OR ‘protein shake*’ OR ‘meal replacement*’ OR ‘carbonated drink*’ OR ‘soft drink*’ OR soda OR sodas OR ‘caffeinated drink*’ OR ‘drinking water’ OR ‘bottled water’ OR ‘carbonated water’ OR ‘sparkling water’ OR ‘flavored water’ OR ‘flavoured water’ OR ‘flavoured drink’ OR ‘flavored drink*’ OR ‘energy drink*’ OR ‘sugar sweetened drink*’ OR juice OR juices OR ‘fruit drink*’ OR ‘fizzy drink*’ OR coffee OR tea OR milk OR soymilk OR buttermilk OR whey OR liquid OR liquids
  - #3 - #1 OR #2
  - #4 - ‘body composition’/exp OR ‘waist circumference’/de OR ‘body height’/de OR ‘obesity’/exp OR ‘body mass’/de
  - #5 - ‘body composition’:ab,ti OR ‘fat mass’:ab,ti OR ‘fat free mass’:ab,ti OR ‘healthy weight’:ab,ti OR underweight:ab,ti OR wasting:ab,ti OR ‘failure to thrive’:ab,ti OR ‘waist circumference’:ab,ti OR ‘head circumference’:ab,ti OR ‘arm circumference’:ab,ti OR ‘thigh circumference’:ab,ti OR ‘neck circumference’:ab,ti OR ‘body height’:ab,ti OR stunting:ab,ti OR stunted:ab,ti OR overweight:ab,ti OR obesity:ab,ti OR obese:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR ‘body fat’:ab,ti
  - #6 - #4 OR #5
  - #7 - #3 AND #6
  - #8 - #3 AND #6 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 33 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results^lxix^

This flow chart illustrates the literature search and screening results for articles examining the relationship between beverage consumption and growth, size, body composition, and risk of overweight and obesity. The literature search yielded 17,060 articles. During title screening, 13,001 articles were screened out. During abstract screening, 2807 articles were screened out. During full-text screening, 1111 articles were screened out. During the hand search, 11 additional articles were identified to include. A total of 152 articles were included in the systematic review at the end of the search and screening process.

### Included articles

1 Zheng M, Allman-Farinelli M, Heitmann BL, . Liquid versus solid energy intake in relation to body composition among Australian children. J Hum Nutr Diet. 2015;28 Suppl 2:70–79. doi: 10.1111/jhn.12223.24548259
2 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Higher longitudinal milk intakes are associated with increased height in a birth cohort followed for 17 years. J Nutr. 2018;148(7):1144–1149. doi: 10.1093/jn/nxy071.29924327
3 Arnberg K, Molgaard C, Michaelsen KF, Jensen SM, Trolle E, Larnkjaer A. Skim milk, whey, and casein increase body weight and whey and casein increase the plasma C-peptide concentration in overweight adolescents. J Nutr. 2012;142(12):2083–2090. doi: 10.3945/jn.112.161208.23077192
4 Babio N, Becerra-Tomas N, Martinez-Gonzalez MA, . Consumption of yogurt, low-fat milk, and other low-fat dairy products is associated with lower risk of metabolic syndrome incidence in an elderly Mediterranean population. J Nutr. 2015;145(10):2308–2316. doi: 10.3945/jn.115.214593.26290009
5 Barr SI, McCarron DA, Heaney RP, . Effects of increased consumption of fluid milk on energy and nutrient intake, body weight, and cardiovascular risk factors in healthy older adults. J Am Diet Assoc. 2000;100(7):810–817. doi: 10.1016/s0002-8223(00)00236-4.10916520
6 Berkey CS, Colditz GA, Rockett HR, Frazier AL, Willett WC. Dairy consumption and female height growth: prospective cohort study. Cancer Epidemiol Biomarkers Prev. 2009;18(6):1881–1887. doi: 10.1158/1055-9965.Epi-08-1163.19505921
7 Berkey CS, Rockett HR, Field AE, Gillman MW, Colditz GA. Sugar-added beverages and adolescent weight change. Obes Res. 2004;12(5):778–788. doi: 10.1038/oby.2004.94.15166298
8 Berkey CS, Rockett HR, Willett WC, Colditz GA. Milk, dairy fat, dietary calcium, and weight gain: a longitudinal study of adolescents. Arch Pediatr Adolesc Med. 2005;159(6):543–550. doi: 10.1001/archpedi.159.6.543.15939853
9 Bes-Rastrollo M, van Dam RM, Martinez-Gonzalez MA, Li TY, Sampson LL, Hu FB. Prospective study of dietary energy density and weight gain in women. Am J Clin Nutr. 2008;88(3):769–777. doi: 10.1093/ajcn/88.3.769.18779295
10 Beydoun MA, Fanelli-Kuczmarski MT, Beydoun HA, . Dairy product consumption and its association with metabolic disturbance in a prospective study of urban adults. Br J Nutr. 2018;119(6):706–719. doi: 10.1017/s0007114518000028.29553032
11 Blum JW, Jacobsen DJ, Donnelly JE. Beverage consumption patterns in elementary school aged children across a two-year period. J Am Coll Nutr. 2005;24(2):93–98. doi: 10.1080/07315724.2005.10719449.15798075
12 Chee WS, Suriah AR, Chan SP, Zaitun Y, Chan YM. The effect of milk supplementation on bone mineral density in postmenopausal Chinese women in Malaysia. Osteoporos Int. 2003;14(10):828–834. doi: 10.1007/s00198-003-1448-6.12915959
13 Daly RM, Brown M, Bass S, Kukuljan S, Nowson C. Calcium- and vitamin D3-fortified milk reduces bone loss at clinically relevant skeletal sites in older men: a 2-year randomized controlled trial. J Bone Miner Res. 2006;21(3):397–405. doi: 10.1359/jbmr.051206.16491287
14 DeBoer MD, Agard HE, Scharf RJ. Milk intake, height and body mass index in preschool children. Arch Dis Child. 2015;100(5):460–465. doi: 10.1136/archdischild-2014-306958.25512962
15 Dong D, Bilger M, van Dam RM, Finkelstein EA. Consumption of specific foods and beverages and excess weight gain among children and adolescents. Health Aff. 2015;34(11):1940–1948. doi: 10.1377/hlthaff.2015.0434.
16 Drapeau V, Despres JP, Bouchard C, . Modifications in food-group consumption are related to long-term body-weight changes. Am J Clin Nutr. 2004;80(1):29–37. doi: 10.1093/ajcn/80.1.29.15213024
17 Dubois L, Diasparra M, Bogl LH, . Dietary intake at 9 years and subsequent body mass index in adolescent boys and girls: a study of monozygotic twin pairs. Twin Res Hum Genet. 2016;19(1):47–59. doi: 10.1017/thg.2015.97.26810866
18 Duffey KJ, Gordon-Larsen P, Steffen LM, Jacobs DR, Jr., Popkin BM. Drinking caloric beverages increases the risk of adverse cardiometabolic outcomes in the Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. 2010;92(4):954–959. doi: 10.3945/ajcn.2010.29478.20702604
19 Faghih S, Abadi AR, Hedayati M, Kimiagar SM. Comparison of the effects of cows’ milk, fortified soy milk, and calcium supplement on weight and fat loss in premenopausal overweight and obese women. Nutr Metab Cardiovasc Dis. 2011;21(7):499–503. doi: 10.1016/j.numecd.2009.11.013.20227261
20 Fathi Y, Faghih S, Zibaeenezhad MJ, Tabatabaei SH. Kefir drink leads to a similar weight loss, compared with milk, in a dairy-rich non-energy-restricted diet in overweight or obese premenopausal women: a randomized controlled trial. Eur J Nutr. 2016;55(1):295–304. doi: 10.1007/s00394-015-0846-9.25648739
21 Fiorito LM, Marini M, Francis LA, Smiciklas-Wright H, Birch LL. Beverage intake of girls at age 5 y predicts adiposity and weight status in childhood and adolescence. Am J Clin Nutr. 2009;90(4):935–942. doi: 10.3945/ajcn.2009.27623.19692492
22 Fresan U, Gea A, Bes-Rastrollo M, Ruiz-Canela M, Martinez-Gonzalez MA. Substitution models of water for other beverages, and the incidence of obesity and weight gain in the SUN cohort. Nutrients. 2016;8(11). doi: 10.3390/nu8110688.
23 Funtikova AN, Subirana I, Gomez SF, . Soft drink consumption is positively associated with increased waist circumference and 10-year incidence of abdominal obesity in Spanish adults. J Nutr. 2015;145(2):328–334. doi: 10.3945/jn.114.205229.25644355
24 Guerendiain M, Villa-Gonzalez E, Barranco-Ruiz Y. Body composition and dairy intake in sedentary employees who participated in a healthy program based on nutrition education and Zumba. Clin Nutr. 2019;38(5):2277–2286. doi: 10.1016/j.clnu.2018.09.032.30342932
25 Guo J, Dougkas A, Elwood PC, Givens DI. Dairy foods and body mass index over 10-year: evidence from the Caerphilly Prospective Cohort Study. Nutrients. 2018;10(10). doi: 10.3390/nu10101515.
26 Haines J, Neumark-Sztainer D, Wall M, Story M. Personal, behavioral, and environmental risk and protective factors for adolescent overweight. Obesity. 2007;15(11):2748–2760. doi: 10.1038/oby.2007.327.18070766
27 Hasnain SR, Singer MR, Bradlee ML, Moore LL. Beverage intake in early childhood and change in body fat from preschool to adolescence. Child Obes. 2014;10(1):42–49. doi: 10.1089/chi.2013.0004.24450382
28 Holmberg S, Thelin A. High dairy fat intake related to less central obesity: a male cohort study with 12 years’ follow-up. Scand J Prim Health Care. 2013;31(2):89–94. doi: 10.3109/02813432.2012.757070.23320900
29 Huh SY, Rifas-Shiman SL, Rich-Edwards JW, Taveras EM, Gillman MW. Prospective association between milk intake and adiposity in preschool-aged children. J Am Diet Assoc. 2010;110(4):563–570. doi: 10.1016/j.jada.2009.12.025.20338282
30 Johansson I, Nilsson LM, Esberg A, Jansson JH, Winkvist A. Dairy intake revisited - associations between dairy intake and lifestyle related cardio-metabolic risk factors in a high milk consuming population. Nutr J. 2018;17(1):110. doi: 10.1186/s12937-018-0418-y.30466440
31 Kaikkonen JE, Mikkila V, Juonala M, . Factors associated with six-year weight change in young and middle-aged adults in the Young Finns Study. Scand J Clin Lab Invest. 2015;75(2):133–144. doi: 10.3109/00365513.2014.992945.25600675
32 Kim D, Kim J. Dairy consumption is associated with a lower incidence of the metabolic syndrome in middle-aged and older Korean adults: the Korean Genome and Epidemiology Study (KoGES). Br J Nutr. 2017;117(1):148–160. doi: 10.1017/s000711451600444x.28098053
33 Kral TV, Stunkard AJ, Berkowitz RI, Stallings VA, Moore RH, Faith MS. Beverage consumption patterns of children born at different risk of obesity. Obesity. 2008;16(8):1802–1808. doi: 10.1038/oby.2008.287.18535546
34 Lambourne K, Washburn RA, Lee J, . A 6-month trial of resistance training with milk supplementation in adolescents: effects on body composition. Int J Sport Nutr Exerc Metab. 2013;23(4):344–356. doi: 10.1123/ijsnem.23.4.344.23239680
35 Larnkjaer A, Arnberg K, Michaelsen KF, Jensen SM, Molgaard C. Effect of milk proteins on linear growth and IGF variables in overweight adolescents. Growth Horm IGF Res. 2014;24(2–3):54–59. doi: 10.1016/j.ghir.2013.12.004.24461794
36 Larnkjaer A, Arnberg K, Michaelsen KF, Jensen SM, Molgaard C. Effect of increased intake of skimmed milk, casein, whey or water on body composition and leptin in overweight adolescents: a randomized trial. Pediatr Obes. 2015;10(6):461–467. doi: 10.1111/ijpo.12007.25612082
37 Laurson K, Eisenmann JC, Moore S. Lack of association between television viewing, soft drinks, physical activity and body mass index in children. Acta Paediatr. 2008;97(6):795–800. doi: 10.1111/j.1651-2227.2008.00713.x.18410467
38 Lee YJ, Seo JA, Yoon T, . Effects of low-fat milk consumption on metabolic and atherogenic biomarkers in Korean adults with the metabolic syndrome: a randomised controlled trial. J Hum Nutr Diet. 2016;29(4):477–486. doi: 10.1111/jhn.12349.26945812
39 Lin SL, Tarrant M, Hui LL, . The role of dairy products and milk in adolescent obesity: evidence from Hong Kong’s “Children of 1997” birth cohort. PLoS One. 2012;7(12):e52575. doi: 10.1371/journal.pone.0052575.23285099
40 Marabujo T, Ramos E, Lopes C. Dairy products and total calcium intake at 13 years of age and its association with obesity at 21 years of age. Eur J Clin Nutr. 2018;72(4):541–547. doi: 10.1038/s41430-017-0082-x.29371641
41 Marshall TA, Curtis AM, Cavanaugh JE, Warren JJ, Levy SM. Child and adolescent sugar-sweetened beverage intakes are longitudinally associated with higher body mass index z scores in a birth cohort followed 17 years. J Acad Nutr Diet. 2019;119(3):425–434. doi: 10.1016/j.jand.2018.11.003.30638821
42 Mozaffarian D, Hao T, Rimm EB, Willett WC, Hu FB. Changes in diet and lifestyle and long-term weight gain in women and men. N Engl J Med. 2011;364(25):2392–2404. doi: 10.1056/NEJMoa1014296.21696306
43 Newby PK, Peterson KE, Berkey CS, Leppert J, Willett WC, Colditz GA. Beverage consumption is not associated with changes in weight and body mass index among low-income preschool children in North Dakota. J Am Diet Assoc. 2004;104(7):1086–1094. doi: 10.1016/j.jada.2004.04.020.15215766
44 Noel SE, Ness AR, Northstone K, Emmett P, Newby PK. Milk intakes are not associated with percent body fat in children from ages 10 to 13 years. J Nutr. 2011;141(11):2035–2041. doi: 10.3945/jn.111.143420.21940511
45 Noel SE, Ness AR, Northstone K, Emmett P, Newby PK. Associations between flavored milk consumption and changes in weight and body composition over time: differences among normal and overweight children. Eur J Clin Nutr. 2013;67(3):295–300. doi: 10.1038/ejcn.2012.123.23031848
46 Pan A, Malik VS, Hao T, Willett WC, Mozaffarian D, Hu FB. Changes in water and beverage intake and long-term weight changes: results from three prospective cohort studies. Int J Obes. 2013;37(10):1378–1385. doi: 10.1038/ijo.2012.225.
47 Pereira MA, Jacobs DR, Jr., Van Horn L, Slattery ML, Kartashov AI, Ludwig DS. Dairy consumption, obesity, and the insulin resistance syndrome in young adults: the CARDIA Study. JAMA. 2002;287(16):2081–2089. doi: 10.1001/jama.287.16.2081.11966382
48 Rautiainen S, Wang L, Lee IM, Manson JE, Buring JE, Sesso HD. Dairy consumption in association with weight change and risk of becoming overweight or obese in middle-aged and older women: a prospective cohort study. Am J Clin Nutr. 2016;103(4):979–988. doi: 10.3945/ajcn.115.118406.26912496
49 Romaguera D, Angquist L, Du H, . Food composition of the diet in relation to changes in waist circumference adjusted for body mass index. PLoS One. 2011;6(8):e23384. doi: 10.1371/journal.pone.0023384.21858094
50 Rosell M, Hakansson NN, Wolk A. Association between dairy food consumption and weight change over 9 y in 19,352 perimenopausal women. Am J Clin Nutr. 2006;84(6):1481–1488. doi: 10.1093/ajcn/84.6.1481.17158433
51 Scharf RJ, Demmer RT, DeBoer MD. Longitudinal evaluation of milk type consumed and weight status in preschoolers. Arch Dis Child. 2013;98(5):335–340. doi: 10.1136/archdischild-2012-302941.23508869
52 Shin H, Yoon YS, Lee Y, Kim CI, Oh SW. Dairy product intake is inversely associated with metabolic syndrome in Korean adults: Anseong and Ansan cohort of the Korean Genome and Epidemiology Study. J Korean Med Sci. 2013;28(10):1482–1488. doi: 10.3346/jkms.2013.28.10.1482.24133353
53 Smith JD, Hou T, Ludwig DS, . Changes in intake of protein foods, carbohydrate amount and quality, and long-term weight change: results from 3 prospective cohorts. Am J Clin Nutr. 2015;101(6):1216–1224. doi: 10.3945/ajcn.114.100867.25854882
54 Snijder MB, van Dam RM, Stehouwer CD, Hiddink GJ, Heine RJ, Dekker JM. A prospective study of dairy consumption in relation to changes in metabolic risk factors: the Hoorn Study. Obesity. 2008;16(3):706–709. doi: 10.1038/oby.2007.93.18239556
55 Striegel-Moore RH, Thompson D, Affenito SG, . Correlates of beverage intake in adolescent girls: the National Heart, Lung, and Blood Institute Growth and Health Study. J Pediatr. 2006;148(2):183–187. doi: 10.1016/j.jpeds.2005.11.025.16492426
56 Vergnaud AC, Peneau S, Chat-Yung S, . Dairy consumption and 6-y changes in body weight and waist circumference in middle-aged French adults. Am J Clin Nutr. 2008;88(5):1248–1255. doi: 10.3945/ajcn.2007.25151.18996859
57 Wagner G, Kindrick S, Hertzler S, DiSilvestro RA. Effects of various forms of calcium on body weight and bone turnover markers in women participating in a weight loss program. J Am Coll Nutr. 2007;26(5):456–461. doi: 10.1080/07315724.2007.10719636.17914134
58 Wang H, Troy LM, Rogers GT, . Longitudinal association between dairy consumption and changes of body weight and waist circumference: the Framingham Heart Study. Int J Obes. 2014;38(2):299–305. doi: 10.1038/ijo.2013.78.
59 Whetstone LM, Kolasa KM, Collier DN. Participation in community-originated interventions is associated with positive changes in weight status and health behaviors in youth. Am J Health Promot. 2012;27(1):10–16. doi: 10.4278/ajhp.100415-QUAN-117.22950920
60 Yang Q, Lin SL, Au Yeung SL, . Genetically predicted milk consumption and bone health, ischemic heart disease and type 2 diabetes: a Mendelian randomization study. Eur J Clin Nutr. 2017;71(8):1008–1012. doi: 10.1038/ejcn.2017.8.28225053
61 Zheng M, Rangan A, Olsen NJ, . Substituting sugar-sweetened beverages with water or milk is inversely associated with body fatness development from childhood to adolescence. Nutrition. 2015;31(1):38–44. doi: 10.1016/j.nut.2014.04.017.25441586
62 Zheng M, Rangan A, Allman-Farinelli M, Rohde JF, Olsen NJ, Heitmann BL. Replacing sugary drinks with milk is inversely associated with weight gain among young obesity-predisposed children. Br J Nutr. 2015;114(9):1448–1455. doi: 10.1017/s0007114515002974.26328600
63 Aptekmann NP, Cesar TB. Orange juice improved lipid profile and blood lactate of overweight middle-aged women subjected to aerobic training. Maturitas. 2010;67(4):343–347. doi: 10.1016/j.maturitas.2010.07.009.20729016
64 Auerbach BJ, Littman AJ, Krieger J, . Association of 100% fruit juice consumption and 3-year weight change among postmenopausal women in the in the Women’s Health Initiative. Prev Med. 2018;109:8–10. doi: 10.1016/j.ypmed.2018.01.004.29330029
65 Cahill JM, Freeland-Graves JH, Shah BS, Lu H, Pepper MR. Determinants of weight loss after an intervention in low-income women in early postpartum. J Am Coll Nutr. 2012;31(2):133–143. doi: 10.1080/07315724.2012.10720019.22855919
66 Carlson JA, Crespo NC, Sallis JF, Patterson RE, Elder JP. Dietary-related and physical activity-related predictors of obesity in children: a 2-year prospective study. Child Obes. 2012;8(2):110–115. doi: 10.1089/chi.2011.0071.22799510
67 Faith MS, Dennison BA, Edmunds LS, Stratton HH. Fruit juice intake predicts increased adiposity gain in children from low-income families: weight status-by-environment interaction. Pediatrics. 2006;118(5):2066–2075. doi: 10.1542/peds.2006-1117.17079580
68 Ferreira-Pego C, Babio N, Bes-Rastrollo M, . Frequent consumption of sugar- and artificially sweetened beverages and natural and bottled fruit juices is associated with an increased risk of metabolic syndrome in a Mediterranean population at high cardiovascular disease risk. J Nutr. 2016;146(8):1528–1536. doi: 10.3945/jn.116.230367.27358413
69 Field AE, Gillman MW, Rosner B, Rockett HR, Colditz GA. Association between fruit and vegetable intake and change in body mass index among a large sample of children and adolescents in the United States. Int J Obes Relat Metab Disord. 2003;27(7):821–826. doi: 10.1038/sj.ijo.0802297.12821968
70 Guerrero AD, Mao C, Fuller B, Bridges M, Franke T, Kuo AA. Racial and ethnic disparities in early childhood obesity: growth trajectories in body mass index. J Racial Ethn Health Disparities. 2016;3(1):129–137. doi: 10.1007/s40615-015-0122-y.26896112
71 Halkjaer J, Tjonneland A, Overvad K, Sorensen TI. Dietary predictors of 5-year changes in waist circumference. J Am Diet Assoc. 2009;109(8):1356–1366. doi: 10.1016/j.jada.2009.05.015.19631041
72 Hollis JH, Houchins JA, Blumberg JB, Mattes RD. Effects of concord grape juice on appetite, diet, body weight, lipid profile, and antioxidant status of adults. J Am Coll Nutr. 2009;28(5):574–582. doi: 10.1080/07315724.2009.10719789.20439553
73 Houchins JA, Burgess JR, Campbell WW, . Beverage vs. solid fruits and vegetables: effects on energy intake and body weight. Obesity. 2012;20(9):1844–1850. doi: 10.1038/oby.2011.192.21720441
74 Libuda L, Alexy U, Sichert-Hellert W, . Pattern of beverage consumption and long-term association with body-weight status in German adolescents--results from the DONALD study. Br J Nutr. 2008;99(6):1370–1379. doi: 10.1017/s0007114507862362.18034911
75 Mrdjenovic G, Levitsky DA. Nutritional and energetic consequences of sweetened drink consumption in 6- to 13-year-old children. J Pediatr. 2003;142(6):604–610. doi: 10.1067/mpd.2003.200.12838186
76 Odegaard AO, Koh WP, Arakawa K, Yu MC, Pereira MA. Soft drink and juice consumption and risk of physician-diagnosed incident type 2 diabetes: the Singapore Chinese Health Study. Am J Epidemiol. 2010;171(6):701–708. doi: 10.1093/aje/kwp452.20160170
77 Pourahmadi Z, Mahboob S, Saedisomeolia A, Reykandeh MT. The effect of tomato juice consumption on antioxidant status in overweight and obese females. Women Health. 2015;55(7):795–804. doi: 10.1080/03630242.2015.1050546.26086066
78 Rautiainen S, Wang L, Lee IM, Manson JE, Buring JE, Sesso HD. Higher intake of fruit, but not vegetables or fiber, at baseline is associated with lower risk of becoming overweight or obese in middle-aged and older women of normal bmi at baseline. J Nutr. 2015;145(5):960–968. doi: 10.3945/jn.114.199158.25934663
79 Shefferly A, Scharf RJ, DeBoer MD. Longitudinal evaluation of 100% fruit juice consumption on BMI status in 2-5-year-old children. Pediatr Obes. 2016;11(3):221–227. doi: 10.1111/ijpo.12048.26110996
80 Simao TN, Lozovoy MA, Simao AN, . Reduced-energy cranberry juice increases folic acid and adiponectin and reduces homocysteine and oxidative stress in patients with the metabolic syndrome. Br J Nutr. 2013;110(10):1885–1894. doi: 10.1017/s0007114513001207.23750500
81 Skinner JD, Carruth BR. A longitudinal study of children’s juice intake and growth: the juice controversy revisited. J Am Diet Assoc. 2001;101(4):432–437. doi: 10.1016/s0002-8223(01)00111-0.11320948
82 Welsh JA, Cogswell ME, Rogers S, Rockett H, Mei Z, Grummer-Strawn LM. Overweight among low-income preschool children associated with the consumption of sweet drinks: Missouri, 1999-2002. Pediatrics. 2005;115(2):e223–229. doi: 10.1542/peds.2004-1148.15687430
83 Altman M, Cahill Holland J, Lundeen D, . Reduction in food away from home is associated with improved child relative weight and body composition outcomes and this relation is mediated by changes in diet quality. J Acad Nutr Diet. 2015;115(9):1400–1407. doi: 10.1016/j.jand.2015.03.009.25963602
84 Alviso-Orellana C, Estrada-Tejada D, Carrillo-Larco RM, Bernabe-Ortiz A. Sweetened beverages, snacks and overweight: findings from the Young Lives cohort study in Peru. Public Health Nutr. 2018;21(9):1627–1633. doi: 10.1017/s1368980018000320.29554988
85 Ambrosini GL, Oddy WH, Huang RC, Mori TA, Beilin LJ, Jebb SA. Prospective associations between sugar-sweetened beverage intakes and cardiometabolic risk factors in adolescents. Am J Clin Nutr. 2013;98(2):327–334. doi: 10.3945/ajcn.112.051383.23719557
86 Appelhans BM, Baylin A, Huang MH, . Beverage intake and metabolic syndrome risk over 14 years: the Study of Women’s Health Across the Nation. J Acad Nutr Diet. 2017;117(4):554–562. doi: 10.1016/j.jand.2016.10.011.27938940
87 Barone Gibbs B, Kinzel LS, Pettee Gabriel K, Chang YF, Kuller LH. Short- and long-term eating habit modification predicts weight change in overweight, postmenopausal women: results from the WOMAN study. J Acad Nutr Diet. 2012;112(9):1347–1355.e1342. doi: 10.1016/j.jand.2012.06.012.22939439
88 Barrio-Lopez MT, Martinez-Gonzalez MA, Fernandez-Montero A, Beunza JJ, Zazpe I, Bes-Rastrollo M. Prospective study of changes in sugar-sweetened beverage consumption and the incidence of the metabolic syndrome and its components: the SUN cohort. Br J Nutr. 2013;110(9):1722–1731. doi: 10.1017/s0007114513000822.23534417
89 Bigornia SJ, LaValley MP, Noel SE, Moore LL, Ness AR, Newby PK. Sugar-sweetened beverage consumption and central and total adiposity in older children: a prospective study accounting for dietary reporting errors. Public Health Nutr. 2015;18(7):1155–1163. doi: 10.1017/s1368980014001700.25166959
90 Boggs DA, Rosenberg L, Coogan PF, Makambi KH, Adams-Campbell LL, Palmer JR. Restaurant foods, sugar-sweetened soft drinks, and obesity risk among young African American women. Ethn Dis. 2013;23(4):445–451. doi. https://www.ncbi.nlm.nih.gov/pubmed/24392607. Published 2014/01/08.24392607
91 Bundrick SC, Thearle MS, Venti CA, Krakoff J, Votruba SB. Soda consumption during ad libitum food intake predicts weight change. J Acad Nutr Diet. 2014;114(3):444–449. doi: 10.1016/j.jand.2013.09.016.24321742
92 Campos V, Despland C, Brandejsky V, . Sugar- and artificially sweetened beverages and intrahepatic fat: A randomized controlled trial. Obesity. 2015;23(12):2335–2339. doi: 10.1002/oby.21310.26727115
93 Cantoral A, Tellez-Rojo MM, Ettinger AS, Hu H, Hernandez-Avila M, Peterson K. Early introduction and cumulative consumption of sugar-sweetened beverages during the pre-school period and risk of obesity at 8-14 years of age. Pediatr Obes. 2016;11(1):68–74. doi: 10.1111/ijpo.12023.25891908
94 Carroll SJ, Niyonsenga T, Coffee NT, Taylor AW, Daniel M. Associations between local descriptive norms for overweight/obesity and insufficient fruit intake, individual-level diet, and 10-year change in body mass index and glycosylated haemoglobin in an Australian cohort. Int J Behav Nutr Phys Act. 2018;15(1):44. doi: 10.1186/s12966-018-0675-3.29776358
95 Chen JL, Guedes CM, Lung AE. Smartphone-based healthy weight management intervention for Chinese American adolescents: short-term efficacy and factors associated with decreased weight. J Adolesc Health. 2019;64(4):443–449. doi: 10.1016/j.jadohealth.2018.08.022.30409751
96 Cleland VJ, Patterson K, Breslin M, Schmidt MD, Dwyer T, Venn AJ. Longitudinal associations between TV viewing and BMI not explained by the ‘mindless eating’ or ‘physical activity displacement’ hypotheses among adults. BMC Public Health. 2018;18(1):797. doi: 10.1186/s12889-018-5674-4.29940922
97 De Coen V, De Bourdeaudhuij I, Verbestel V, Maes L, Vereecken C. Risk factors for childhood overweight: a 30-month longitudinal study of 3- to 6-year-old children. Public Health Nutr. 2014;17(9):1993–2000. doi: 10.1017/s1368980013002346.24172063
98 de Ruyter JC, Olthof MR, Seidell JC, Katan MB. A trial of sugar-free or sugar-sweetened beverages and body weight in children. N Engl J Med. 2012;367(15):1397–1406. doi: 10.1056/NEJMoa1203034.22998340
99 DeBoer MD, Scharf RJ, Demmer RT. Sugar-sweetened beverages and weight gain in 2- to 5-year-old children. Pediatrics. 2013;132(3):413–420. doi: 10.1542/peds.2013-0570.23918897
100 Durao C, Severo M, Oliveira A, . Evaluating the effect of energy-dense foods consumption on preschool children’s body mass index: a prospective analysis from 2 to 4 years of age. Eur J Nutr. 2015;54(5):835–843. doi: 10.1007/s00394-014-0762-4.25185968
101 Ebbeling CB, Feldman HA, Chomitz VR, . A randomized trial of sugar-sweetened beverages and adolescent body weight. N Engl J Med. 2012;367(15):1407–1416. doi: 10.1056/NEJMoa1203388.22998339
102 Enes CC, Slater B. Variation in dietary intake and physical activity pattern as predictors of change in body mass index (BMI) Z-score among Brazilian adolescents. Rev Bras Epidemiol. 2013;16(2):493–501. doi: 10.1590/s1415-790x2013000200023.24142019
103 Field AE, Sonneville KR, Falbe J, . Association of sports drinks with weight gain among adolescents and young adults. Obesity. 2014;22(10):2238–2243. doi: 10.1002/oby.20845.25044989
104 Fowler SP, Williams K, Hazuda HP. Diet soda intake is associated with long-term increases in waist circumference in a biethnic cohort of older adults: the San Antonio Longitudinal Study of Aging. J Am Geriatr Soc. 2015;63(4):708–715. doi: 10.1111/jgs.13376.25780952
105 French SA, Mitchell NR, Hannan PJ. Decrease in television viewing predicts lower body mass index at 1-year follow-up in adolescents, but not adults. J Nutr Educ Behav. 2012;44(5):415–422. doi: 10.1016/j.jneb.2011.12.008.22591582
106 Gearon E, Peeters A, Ng W, Hodge A, Backholer K. Diet and physical activity as possible mediators of the association between educational attainment and body mass index gain among Australian adults. Int J Public Health. 2018;63(7):883–893. doi: 10.1007/s00038-018-1100-z.29687156
107 Gopinath B, Flood VM, Rochtchina E, . Carbohydrate nutrition and development of adiposity during adolescence. Obesity. 2013;21(9):1884–1890. doi: 10.1002/oby.20405.23519919
108 Higgins KA, Mattes RD. A randomized controlled trial contrasting the effects of 4 low-calorie sweeteners and sucrose on body weight in adults with overweight or obesity. Am J Clin Nutr. 2019;109(5):1288–1301. doi: 10.1093/ajcn/nqy381.30997499
109 Hooley M, Skouteris H, Millar L. The relationship between childhood weight, dental caries and eating practices in children aged 4-8 years in Australia, 2004-2008. Pediatr Obes. 2012;7(6):461–470. doi: 10.1111/j.2047-6310.2012.00072.x.22911896
110 Jensen BW, Nichols M, Allender S, . Inconsistent associations between sweet drink intake and 2-year change in BMI among Victorian children and adolescents. Pediatr Obes. 2013;8(4):271–283. doi: 10.1111/j.2047-6310.2013.00174.x.23785025
111 Jensen BW, Nielsen BM, Husby I, . Association between sweet drink intake and adiposity in Danish children participating in a long-term intervention study. Pediatr Obes. 2013;8(4):259–270. doi: 10.1111/j.2047-6310.2013.00170.x.23630030
112 Johnson BA, Kremer PJ, Swinburn BA, de Silva-Sanigorski AM. Multilevel analysis of the Be Active Eat Well intervention: environmental and behavioural influences on reductions in child obesity risk. Int J Obes. 2012;36(7):901–907. doi: 10.1038/ijo.2012.23.
113 Kang Y, Kim J. Soft drink consumption is associated with increased incidence of the metabolic syndrome only in women. Br J Nutr. 2017;117(2):315–324. doi: 10.1017/s0007114517000046.28166856
114 Karkkainen U, Mustelin L, Raevuori A, Kaprio J, Keski-Rahkonen A. Successful weight maintainers among young adults-A ten-year prospective population study. Eat Behav. 2018;29:91–98. doi: 10.1016/j.eatbeh.2018.03.004.29549864
115 Katan MB, de Ruyter JC, Kuijper LD, Chow CC, Hall KD, Olthof MR. Impact of masked replacement of sugar-sweetened with sugar-free beverages on body weight increases with initial bmi: secondary analysis of data from an 18 month double-blind trial in children. PLoS One. 2016;11(7):e0159771. doi: 10.1371/journal.pone.0159771.27447721
116 Laska MN, Murray DM, Lytle LA, Harnack LJ. Longitudinal associations between key dietary behaviors and weight gain over time: transitions through the adolescent years. Obesity. 2012;20(1):118–125. doi: 10.1038/oby.2011.179.21701567
117 Lee AK, Chowdhury R, Welsh JA. Sugars and adiposity: the long-term effects of consuming added and naturally occurring sugars in foods and in beverages. Obes Sci Pract. 2015;1(1):41–49. doi: 10.1002/osp4.7.27774248
118 Ma J, McKeown NM, Hwang SJ, Hoffmann U, Jacques PF, Fox CS. Sugar-sweetened beverage consumption is associated with change of visceral adipose tissue over 6 years of follow-up. Circulation. 2016;133(4):370–377. doi: 10.1161/circulationaha.115.018704.26755505
119 Macintyre AK, Marryat L, Chambers S. Exposure to liquid sweetness in early childhood: artificially-sweetened and sugar-sweetened beverage consumption at 4-5 years and risk of overweight and obesity at 7-8 years. Pediatr Obes. 2018;13(12):755–765. doi: 10.1111/ijpo.12284.29624909
120 Maersk M, Belza A, Stodkilde-Jorgensen H, . Sucrose-sweetened beverages increase fat storage in the liver, muscle, and visceral fat depot: a 6-mo randomized intervention study. Am J Clin Nutr. 2012;95(2):283–289. doi: 10.3945/ajcn.111.022533.22205311
121 Millar L, Rowland B, Nichols M, . Relationship between raised BMI and sugar sweetened beverage and high fat food consumption among children. Obesity. 2014;22(5):E96–103. doi: 10.1002/oby.20665.24318968
122 Mirmiran P, Yuzbashian E, Asghari G, Hosseinpour-Niazi S, Azizi F. Consumption of sugar sweetened beverage is associated with incidence of metabolic syndrome in Tehranian children and adolescents. Nutr Metab. 2015;12:25. doi: 10.1186/s12986-015-0021-6.
123 Muckelbauer R, Gortmaker SL, Libuda L, . Changes in water and sugar-containing beverage consumption and body weight outcomes in children. Br J Nutr. 2016;115(11):2057–2066. doi: 10.1017/s0007114516001136.27040694
124 Olsen NJ, Andersen LB, Wedderkopp N, Kristensen PL, Heitmann BL. Intake of liquid and solid sucrose in relation to changes in body fatness over 6 years among 8- to 10-year-old children: the European Youth Heart Study. Obes Facts. 2012;5(4):506–512. doi: 10.1159/000341631.22854439
125 Olsen NJ, Angquist L, Larsen SC, . Interactions between genetic variants associated with adiposity traits and soft drinks in relation to longitudinal changes in body weight and waist circumference. Am J Clin Nutr. 2016;104(3):816–826. doi: 10.3945/ajcn.115.122820.27465380
126 Partridge SR, McGeechan K, Bauman A, Phongsavan P, Allman-Farinelli M. Improved eating behaviours mediate weight gain prevention of young adults: moderation and mediation results of a randomised controlled trial of TXT2BFiT, mHealth program. Int J Behav Nutr Phys Act. 2016;13:44. doi: 10.1186/s12966-016-0368-8.27039178
127 Qi Q, Chu AY, Kang JH, . Sugar-sweetened beverages and genetic risk of obesity. N Engl J Med. 2012;367(15):1387–1396. doi: 10.1056/NEJMoa1203039.22998338
128 Seo DC, King MH, Kim N, Sovinski D, Meade R, Lederer AM. Predictors for persistent overweight, deteriorated weight status, and improved weight status during 18 months in a school-based longitudinal cohort. Am J Health Promot. 2015;30(1):22–27. doi: 10.4278/ajhp.131118-QUAN-585.25372231
129 Shroff MR, Perng W, Baylin A, Mora-Plazas M, Marin C, Villamor E. Adherence to a snacking dietary pattern and soda intake are related to the development of adiposity: a prospective study in school-age children. Public Health Nutr. 2014;17(7):1507–1513. doi: 10.1017/s136898001300133x.23701749
130 Sichieri R, Yokoo EM, Pereira RA, Veiga GV. Water and sugar-sweetened beverage consumption and changes in BMI among Brazilian fourth graders after 1-year follow-up. Public Health Nutr. 2013;16(1):73–77. doi: 10.1017/s1368980012001309.22640686
131 Stern D, Middaugh N, Rice MS, . Changes in sugar-sweetened soda consumption, weight, and waist circumference: 2-year cohort of Mexican women. Am J Public Health. 2017;107(11):1801–1808. doi: 10.2105/ajph.2017.304008.28933937
132 Stoof SP, Twisk JW, Olthof MR. Is the intake of sugar-containing beverages during adolescence related to adult weight status? Public Health Nutr. 2013;16(7):1257–1262. doi: 10.1017/s1368980011002783.22067526
133 Tate DF, Turner-McGrievy G, Lyons E, . Replacing caloric beverages with water or diet beverages for weight loss in adults: main results of the Choose Healthy Options Consciously Everyday (CHOICE) randomized clinical trial. Am J Clin Nutr. 2012;95(3):555–563. doi: 10.3945/ajcn.111.026278.22301929
134 Thurber KA, Dobbins T, Neeman T, Banwell C, Banks E. Body mass index trajectories of Indigenous Australian children and relation to screen time, diet, and demographic factors. Obesity. 2017;25(4):747–756. doi: 10.1002/oby.21783.28349661
135 Traub M, Lauer R, Kesztyus T, Wartha O, Steinacker JM, Kesztyus D. Skipping breakfast, overconsumption of soft drinks and screen media: longitudinal analysis of the combined influence on weight development in primary schoolchildren. BMC Public Health. 2018;18(1):363. doi: 10.1186/s12889-018-5262-7.29548323
136 Tucker LA, Tucker JM, Bailey BW, LeCheminant JD. A 4-year prospective study of soft drink consumption and weight gain: the role of calorie intake and physical activity. Am J Health Promot. 2015;29(4):262–265. doi: 10.4278/ajhp.130619-ARB-315.24717069
137 Vazquez-Duran M, Orea-Tejeda A, Castillo-Martinez L, Cano-Garcia A, Tellez-Olvera L, Keirns-Davis C. A randomized control trial for reduction of caloric and non-caloric sweetened beverages in young adults: effects in weight, body composition and blood pressure. Nutr Hosp. 2016;33(6):1372–1378. doi: 10.20960/nh.797.28000468
138 Wheaton N, Millar L, Allender S, Nichols M. The stability of weight status through the early to middle childhood years in Australia: a longitudinal study. BMJ Open. 2015;5(4):e006963. doi: 10.1136/bmjopen-2014-006963.
139 Yiotaldiotariotam M, Singh AS, te Velde SJ, . Mediators of longitudinal changes in measures of adiposity in teenagers using parallel process latent growth modeling. Obesity. 2013;21(11):2387–2395. doi: 10.1002/oby.20463.23794531
140 Zheng M, Rangan A, Olsen NJ, . Sugar-sweetened beverages consumption in relation to changes in body fatness over 6 and 12 years among 9-year-old children: the European Youth Heart Study. Eur J Clin Nutr. 2014;68(1):77–83. doi: 10.1038/ejcn.2013.243.24281311
141 Zulfiqar T, Strazdins L, Dinh H, Banwell C, D’Este C. Drivers of overweight/obesity in 4-11 year old children of Australians and immigrants; evidence from growing up in Australia. J Immigr Minor Health. 2019;21(4):737–750. doi: 10.1007/s10903-018-0841-3.30484000
142 Bonnet F, Tavenard A, Esvan M, . Consumption of a carbonated beverage with high-intensity sweeteners has no effect on insulin sensitivity and secretion in nondiabetic adults. J Nutr. 2018;148(8):1293–1299. doi: 10.1093/jn/nxy100.29982723
143 Davis JN, Asigbee FM, Markowitz AK, . Consumption of artificial sweetened beverages associated with adiposity and increasing HbA1c in Hispanic youth. Clin Obes. 2018;8(4):236–243. doi: 10.1111/cob.12260.29896938
144 Duffey KJ, Steffen LM, Van Horn L, Jacobs DR, Jr., Popkin BM. Dietary patterns matter: diet beverages and cardiometabolic risks in the longitudinal Coronary Artery Risk Development in Young Adults (CARDIA) Study. Am J Clin Nutr. 2012;95(4):909–915. doi: 10.3945/ajcn.111.026682.22378729
145 Hinkle SN, Rawal S, Bjerregaard AA, . A prospective study of artificially sweetened beverage intake and cardiometabolic health among women at high risk. Am J Clin Nutr. 2019;110(1):221–232. doi: 10.1093/ajcn/nqz094.31172169
146 Ludwig DS, Peterson KE, Gortmaker SL. Relation between consumption of sugar-sweetened drinks and childhood obesity: a prospective, observational analysis. Lancet. 2001;357(9255):505–508. doi: 10.1016/s0140-6736(00)04041-1.11229668
147 Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects on weight loss in adults of replacing diet beverages with water during a hypoenergetic diet: a randomized, 24-wk clinical trial. Am J Clin Nutr. 2015;102(6):1305–1312. doi: 10.3945/ajcn.115.109397.26537940
148 Madjd A, Taylor MA, Delavari A, Malekzadeh R, Macdonald IA, Farshchi HR. Effects of replacing diet beverages with water on weight loss and weight maintenance: 18-month follow-up, randomized clinical trial. Int J Obes. 2018;42(4):835–840. doi: 10.1038/ijo.2017.306.
149 Nettleton JA, Lutsey PL, Wang Y, Lima JA, Michos ED, Jacobs DR, Jr. Diet soda intake and risk of incident metabolic syndrome and type 2 diabetes in the Multi-Ethnic Study of Atherosclerosis (MESA). Diabetes Care. 2009;32(4):688–694. doi: 10.2337/dc08-1799.19151203
150 Peters JC, Beck J, Cardel M, . The effects of water and non-nutritive sweetened beverages on weight loss and weight maintenance: A randomized clinical trial. Obesity. 2016;24(2):297–304. doi: 10.1002/oby.21327.26708700
151 Peters JC, Wyatt HR, Foster GD, . The effects of water and non-nutritive sweetened beverages on weight loss during a 12-week weight loss treatment program. Obesity. 2014;22(6):1415–1421. doi: 10.1002/oby.20737.24862170
152 Schulze MB, Manson JE, Ludwig DS, . Sugar-sweetened beverages, weight gain, and incidence of type 2 diabetes in young and middle-aged women. JAMA. 2004;292(8):927–934. doi: 10.1001/jama.292.8.927.15328324

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes columns for the categories of inclusion and exclusion criteria (see Table 32) that studies were excluded based on. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons. Information about articles excluded after title and abstract screening is available upon request.

Table 33 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | Adam, S, Westenhoefer, J, Rudolphi, B, Kraaibeek, HK. Three- and five-year follow-up of a combined inpatient-outpatient treatment of obese children and adolescents. Int J Pediatr. 2013. 2013:856743. doi:10.1155/2013/856743. | Intervention/exposure
2 | Adams, A, LaRowe, T, Cronin, KA, Prince, RJ, Jobe, JB. Healthy children, strong families: results of a randomized trial of obesity prevention for preschool American Indian children and their families. Obesity (silver spring, md.). 2011. 19:S110-. doi:10.1038/oby.2011.226. | Publication status
3 | Adams, A, Receveur, O, Mundt, M, Paradis, G, Macaulay, AC. Healthy lifestyle indicators in children (grades 4 to 6) from the Kahnawake Schools Diabetes Prevention Project. Canadian Journal of Diabetes. 2005. 29:403-409. | Study design
4 | Aeberli, I, Gerber, PA, Hochuli, M, Haile, S, Gouni-Berthold, I, Berthold, HK, Spinas, GA, Berneis, K. Low to moderate consumption of sugar-sweetened beverages impairs glucose and lipid metabolism and promotes inflammation in healthy young men - A randomized, controlled trial. Obesity reviews. 2011. 12:54-55. doi:10.1111/j.1467-789X.2011.00888.x. | Intervention/exposure; Comparator
5 | Afzalpour, ME, Ghasemi, E, Zarban, A. Effects of 10 weeks of high intensity interval training and green tea supplementation on serum levels of Sirtuin-1 and peroxisome proliferator-activated receptor gamma co-activator 1-alpha in overweight women. Science and Sports. 2017. 32:82-90. doi:10.1016/j.scispo.2016.09.004. | Intervention/exposure
6 | Agerholm-Larsen, L, Raben, A, Haulrik, N, Hansen, AS, Manders, M, Astrup, A. Effect of 8 week intake of probiotic milk products on risk factors for cardiovascular diseases. Eur J Clin Nutr. 2000. 54:288-97. | Intervention/exposure
7 | Agin, D, Kotler, DP, Papandreou, D, Liss, M, Wang, J, Thornton, J, Gallagher, D, Pierson, RN, Jr. Effects of whey protein and resistance exercise on body composition and muscle strength in women with HIV infection. Ann N Y Acad Sci. 2000. 904:607-9. doi:10.1111/j.1749-6632.2000.tb06523.x. | Health status
8 | Agudelo-Ochoa, GM, Pulgarin-Zapata, IC, Velasquez-Rodriguez, CM, Duque-Ramirez, M, Naranjo-Cano, M, Quintero-Ortiz, MM, Lara-Guzman, OJ, Munoz-Durango, K. Coffee Consumption Increases the Antioxidant Capacity of Plasma and Has No Effect on the Lipid Profile or Vascular Function in Healthy Adults in a Randomized Controlled Trial. J Nutr. 2016. 146:524-31. doi:10.3945/jn.115.224774. | Outcome
9 | Ahmad, R, Mok, A, Rangan, AM, Louie, JCY. Association of free sugar intake with blood pressure and obesity measures in Australian adults. Eur J Nutr. 2019. doi:10.1007/s00394-019-01932-7. | Study design
10 | Aiso, I, Inoue, H, Seiyama, Y, Kuwano, T. Compared with the intake of commercial vegetable juice, the intake of fresh fruit and komatsuna (Brassica rapa L. var. perviridis) juice mixture reduces serum cholesterol in middle-aged men: a randomized controlled pilot study. Lipids Health Dis. 2014. 13:102. doi:10.1186/1476-511x-13-102. | Comparator
11 | Aizawa, T, Yamamoto, A, Ueno, T. Effect of oral theaflavin administration on body weight, fat, and muscle in healthy subjects: a randomized pilot study. Biosci Biotechnol Biochem. 2017. 81:311-315. doi:10.1080/09168451.2016.1246170. | Intervention/exposure
12 | Akazome, Y, Kametani, N, Kanda, T, Shimasaki, H, Kobayashi, S. Evaluation of safety of excessive intake and efficacy of long-term intake of beverages containing apple polyphenols. J Oleo Sci. 2010. 59:321-38. | Comparator
13 | Akazome, Y, Kanda, T, Ohtake, Y, Hashimoto, H, Kametani, N, Sato, K, Nakamura, T, Kajimoto, Y. Evaluation of safety of excessive intake and efficacy of long term intake of beverage containing polyphenols derived from apples. Japanese pharmacology and therapeutics. 2005. 33:893-911. | Language
14 | Albala, C, Ebbeling, CB, Cifuentes, M, Lera, L, Bustos, N, Ludwig, DS. Effects of replacing the habitual consumption of sugar-sweetened beverages with milk in Chilean children. Am J Clin Nutr. 2008. 88:605-11. doi:10.1093/ajcn/88.3.605. | Intervention/exposure
15 | Alderete, E, Bejarano, I, Rodriguez, A. Beverage intake and obesity in early childhood: evidence form primary health care clients in Northwest Argentina. J Dev Orig Health Dis. 2016. 7:244-252. doi:10.1017/s204017441500793x. | Study design
16 | Aldrich, ND, Reicks, MM, Sibley, SD, Redmon, JB, Thomas, W, Raatz, SK. Varying protein source and quantity do not significantly improve weight loss, fat loss, or satiety in reduced energy diets among midlife adults. Nutr Res. 2011. 31:104-12. doi:10.1016/j.nutres.2011.01.004. | Intervention/exposure
17 | Alexy, U, Reinehr, T, Sichert-Hellert, W, Wollenhaupt, A, Kersting, M, Andler, W. Positive changes of dietary habits after an outpatient training program for overweight children. Nutrition Research. 2006. 26:202-208. doi:10.1016/j.nutres.2006.05.007. | Intervention/exposure
18 | Al-Haggar, M, Yahia, N, Ghanem, H. High dairy calcium intake in pubertal girls: Relation to weight gain and bone mineral status. Journal of Medical Sciences. 2006. 6:631-635. | Intervention/exposure
19 | Alhamhany, NN, Alassady, EH. Does green coffee has a positive effect on body mass index and lipid profile in a sample of obese people. Journal of Pharmaceutical Sciences and Research. 2018. 10:627-630. | Intervention/exposure; Country
20 | Ali, A, Yazaki, Y, Njike, VY, Ma, Y, Katz, DL. Effect of fruit and vegetable concentrates on endothelial function in metabolic syndrome: A randomized controlled trial. Nutrition Journal. 2011. 10. doi:10.1186/1475-2891-10-72. | Intervention/exposure
21 | Allison, DB, Gadbury, G, Schwartz, LG, Murugesan, R, Kraker, JL, Heshka, S, Fontaine, KR, Heymsfield, SB. A novel soy-based meal replacement formula for weight loss among obese individuals: a randomized controlled clinical trial. Eur J Clin Nutr. 2003. 57:514-22. doi:10.1038/sj.ejcn.1601587. | Intervention/exposure
22 | Al-Naggar, RA, Osman, MT, Abdulghani, M. Effects green tea on the body weight of malaysian young obese females: Single blinded clinical trail study. Research Journal of Pharmaceutical, Biological and Chemical Sciences. 2013. 4:1649-1655. | Intervention/exposure
23 | Alonso, A, Zozaya, C, Vazquez, Z, Alfredo Martinez, J, Martinez-Gonzalez, MA. The effect of low-fat versus whole-fat dairy product intake on blood pressure and weight in young normotensive adults. J Hum Nutr Diet. 2009. 22:336-42. doi:10.1111/j.1365-277X.2009.00967.x. | Intervention/exposure
24 | Alperet, DJ, Rebello, SA, Khoo, Ey-H, Tay, Z, Seah, Ss-Y, Tai, BC, Tai, ES, Emady-Azar, S, Chou, CJ, Darimont, C, etal, . The effects of coffee consumption on insulin sensitivity and other risk factors for type 2 diabetes. Circulation. 2018. 137. | Publication status
25 | Alves, NE, Enes, BN, Martino, HS, Alfenas Rde, C, Ribeiro, SM. Meal replacement based on Human Ration modulates metabolic risk factors during body weight loss: a randomized controlled trial. Eur J Nutr. 2014. 53:939-50. doi:10.1007/s00394-013-0598-3. | Intervention/exposure; Comparator
26 | Amagase, H, Nance, DM. A randomized, double-blind, placebo-controlled, clinical study of the general effects of a standardized Lycium barbarum (Goji) Juice, GoChi. J Altern Complement Med. 2008. 14:403-12. doi:10.1089/acm.2008.0004. | Intervention/exposure; Comparator
27 | Amagase, H, Nance, DM. A randomized, double-blind, placebo-controlled, clinical study of the general effects of a standardized Lycium barbarum (goji) juice, GoChi™. Journal of Alternative and Complementary Medicine. 2008. 14:403-412. doi:10.1089/acm.2008.0004. | Comparator; Duplicate
28 | Amagase, H, Nance, DM. Lycium barbarum increases caloric expenditure and decreases waist circumference in healthy overweight men and women: pilot study. J Am Coll Nutr. 2011. 30:304-9. | Intervention/exposure; Comparator
29 | Amiot-Carlin, MJ, Morrissey, C, Vinet, A. Vitamin d supplementation associated with lifestyle intervention enhanced the loss of abdominal fat mass in obese adolescents: a double-blind randomized controlled trial (nct02400151). Annals of nutrition & metabolism. 2017. 71:349-350. doi:10.1159/000480486. | Publication status
30 | Amozadeh, H, Shabani, R, Nazari, M. The Effect of Aerobic Training and Green Tea Supplementation on Cardio Metabolic Risk Factors in Overweight and Obese Females: A Randomized Trial. Int J Endocrinol Metab. 2018. 16:e60738. doi:10.5812/ijem.60738. | Intervention/exposure
31 | Andersen, T, Fogh, J. Weight loss and delayed gastric emptying following a South American herbal preparation in overweight patients. J Hum Nutr Diet. 2001. 14:243-50. | Intervention/exposure
32 | Anderson, JW, Fuller, J, Patterson, K, Blair, R, Tabor, A. Soy compared to casein meal replacement shakes with energy-restricted diets for obese women: randomized controlled trial. Metabolism. 2007. 56:280-8. doi:10.1016/j.metabol.2006.10.013. | Health status
33 | Anderson, JW, Hoie, LH. Weight loss and lipid changes with low-energy diets: comparator study of milk-based versus soy-based liquid meal replacement interventions. J Am Coll Nutr. 2005. 24:210-6. | Comparator
34 | Anderson, JW, Reynolds, LR, Bush, HM, Rinsky, JL, Washnock, C. Effect of a behavioral/nutritional intervention program on weight loss in obese adults: a randomized controlled trial. Postgrad Med. 2011. 123:205-13. doi:10.3810/pgm.2011.09.2476. | Health status
35 | Andrade, RG, Chaves, OC, Costa, DA, Andrade, AC, Bispo, S, Felicissimo, MF, Friche, AA, Proietti, FA, Xavier, CC, Caiaffa, WT. Overweight in men and women among urban area residents: individual factors and socioeconomic context. Cad Saude Publica. 2015. 31 Suppl 1:148-58. doi:10.1590/0102-311x00102714. | Study design
36 | Androutsos, O, Moschonis, G, Ierodiakonou, D, Karatzi, K, De Bourdeaudhuij, I, Iotova, V, Zych, K, Moreno, LA, Koletzko, B, Manios, Y. Perinatal and lifestyle factors mediate the association between maternal education and preschool children’s weight status: the ToyBox study. Nutrition. 2018. 48:6-12. doi:10.1016/j.nut.2017.11.006. | Study design; Intervention/exposure; Population at Intervention/exposure
37 | Angeles-Agdeppa, I, Capanzana, MV, Li-Yu, J, Schollum, LM, Kruger, MC. High-calcium milk prevents overweight and obesity among postmenopausal women. Food Nutr Bull. 2010. 31:381-90. doi:10.1177/156482651003100301. | Country; Publication status
38 | Angeles-Agdeppa, I, Magsadia, C. Increased height and cognition after consumption of fortified milk. Annals of nutrition and metabolism.. 2013. 63:951. doi:10.1159/000354245. | Publication status
39 | Angeles-Agdeppa, I, Magsadia, CR, Capanzana, MV. Fortified juice drink improved iron and zinc status of schoolchildren. Asia Pac J Clin Nutr. 2011. 20:535-43. | Country
40 | Angelopoulos, PD, Milionis, HJ, Grammatikaki, E, Moschonis, G, Manios, Y. Changes in BMI and blood pressure after a school based intervention: the CHILDREN study. Eur J Public Health. 2009. 19:319-25. doi:10.1093/eurpub/ckp004. | Intervention/exposure
41 | Angelopoulos, TJ, Lowndes, J, Sinnett, S, Rippe, JM. Fructose Containing Sugars at Normal Levels of Consumption Do Not Effect Adversely Components of the Metabolic Syndrome and Risk Factors for Cardiovascular Disease. Nutrients. 2016. 8:179. doi:10.3390/nu8040179. | Comparator
42 | Annesi, JJ, Walsh, AM, Smith, AE. Effects of 12- and 24-week multimodal interventions on physical activity, nutritional behaviors, and body mass index and its psychological predictors in severely obese adolescents at risk for diabetes. Perm J. 2010. 14:29-37. doi:10.7812/tpp/10-034. | Intervention/exposure; Health status
43 | Annunziato, RA, Timko, CA, Crerand, CE, Didie, ER, Bellace, DL, Phelan, S, Kerzhnerman, I, Lowe, MR. A randomized trial examining differential meal replacement adherence in a weight loss maintenance program after one-year follow-up. Eat Behav. 2009. 10:176-83. doi:10.1016/j.eatbeh.2009.05.003. | Intervention/exposure
44 | Antonio, J, Sanders, MS, Van Gammeren, D. The effects of bovine colostrum supplementation on body composition and exercise performance in active men and women. Nutrition. 2001. 17:243-7. | Intervention/exposure; Comparator
45 | Apovian, C, Bigornia, S, Cullum-Dugan, D, Schoonmaker, C, Radziejowska, J, Phipps, J, Gokce, N, Istfan, N, Meyers, A, Lenders, C. Milk-Based Nutritional Supplements in Conjunction With Lifestyle Intervention in Overweight Adolescents. Infant Child Adolesc Nutr. 2009. 1:37-44. doi:10.1177/1941406408326991. | Study design
46 | Appleton, KM, Conner, MT. Body weight, body-weight concerns and eating styles in habitual heavy users and non-users of artificially sweetened beverages. Appetite. 2001. 37:225-30. doi:10.1006/appe.2001.0435. | Study design
47 | Aptekmann, NP, Cesar, TB. Long-term orange juice consumption is associated with low LDL-cholesterol and apolipoprotein B in normal and moderately hypercholesterolemic subjects. Lipids Health Dis. 2013. 12:119. doi:10.1186/1476-511x-12-119. | Study design
48 | Araki, R, Fujie, K, Yuine, N, Watabe, Y, Nakata, Y, Suzuki, H, Isoda, H, Hashimoto, K. Olive leaf tea is beneficial for lipid metabolism in adults with prediabetes: an exploratory randomized controlled trial. Nutr Res. 2019. 67:60-66. doi:10.1016/j.nutres.2019.05.003. | Intervention/exposure
49 | Arciero, PJ, Baur, D, Connelly, S, Ormsbee, MJ. Timed-daily ingestion of whey protein and exercise training reduces visceral adipose tissue mass and improves insulin resistance: the PRISE study. J Appl Physiol (1985). 2014. 117:1-10. doi:10.1152/japplphysiol.00152.2014. | Intervention/exposure; Comparator
50 | Arciero, PJ, Edmonds, RC, Bunsawat, K, Gentile, CL, Ketcham, C, Darin, C, Renna, M, Zheng, Q, Zhang, JZ, Ormsbee, MJ. Protein-Pacing from Food or Supplementation Improves Physical Performance in Overweight Men and Women: The PRISE 2 Study. Nutrients. 2016. 8. doi:10.3390/nu8050288. | Intervention/exposure; Comparator
51 | Ard, J, Auriemma, A, Coburn, S, Lewis, K, Loper, J, Matarese, L, Periman, S, Pories, W, Rothberg, A. Effectiveness of a total meal replacement program (OPTIFAST® program) compared with a reduced-energy food based diet plan on weight loss: results from the OPTIWIN study. Obesity facts. 2018. 11:337-338. doi:10.1159/000489691. | Publication status
52 | Ard, JD, Cook, M, Rushing, J, Frain, A, Beavers, K, Miller, G, Miller, ME, Nicklas, B. Impact on weight and physical function of intensive medical weight loss in older adults with stage II and III obesity. Obesity (Silver Spring). 2016. 24:1861-6. doi:10.1002/oby.21569. | Intervention/exposure; Health status
53 | Ard, JD, Lewis, KH, Rothberg, A, Auriemma, A, Coburn, SL, Cohen, SS, Loper, J, Matarese, L, Pories, WJ, Periman, S. Effectiveness of Total Meal Replacement Program (OPTIFAST Program) on Weight Loss: results from the OPTIWIN Study. Obesity (silver spring, md.). 2018. (no pagination). doi:10.1002/oby.22303. | Health status; Publication status
54 | Arenaza, L, Munoz-Hernandez, V, Medrano, M, Oses, M, Amasene, M, Merchan-Ramirez, E, Cadenas-Sanchez, C, Ortega, FB, Ruiz, JR, Labayen, I. Association of Breakfast Quality and Energy Density with Cardiometabolic Risk Factors in Overweight/Obese Children: Role of Physical Activity. Nutrients. 2018. 10. doi:10.3390/nu10081066. | Study design
55 | Arentson-Lantz, EJ, Galvan, E, Wacher, A, Paddon-Jones, D. Whey protein protects muscle mass loss of older adults during 7 days of inactivity and accelerates recovery of aerobic fitness during rehabilitation. FASEB journal. 2017. 31. | Publication status
56 | Armborst, D, Metzner, C, Bitterlich, N, Lemperle, M, Siener, R. Effect of a weight-loss stabilization following a weight reduction with or without meal replacement on cardiometabolic risk in overweight women. A randomized controlled trial. Int J Food Sci Nutr. 2019. 70:453-466. doi:10.1080/09637486.2018.1537363. | Intervention/exposure
57 | Arnarson, A, Gudny Geirsdottir, O, Ramel, A, Briem, K, Jonsson, PV, Thorsdottir, I. Effects of whey proteins and carbohydrates on the efficacy of resistance training in elderly people: double blind, randomised controlled trial. Eur J Clin Nutr. 2013. 67:821-6. doi:10.1038/ejcn.2013.40. | Comparator
58 | Arsenault, JE, Mora-Plazas, M, Forero, Y, López-Arana, S, Marín, C, Baylin, A, Villamor, E. Provision of a school snack is associated with vitamin B-12 status, linear growth, and morbidity in children from Bogotá, Colombia. Journal of Nutrition. 2009. 139:1744-1750. doi:10.3945/jn.109.108662. | Intervention/exposure; Country
59 | Arterburn, LM, Coleman, CD, Kiel, J, Kelley, K, Mantilla, L, Frye, N, Sanoshy, K, Cook, CM. Randomized controlled trial assessing two commercial weight loss programs in adults with overweight or obesity. Obes Sci Pract. 2019. 5:3-14. doi:10.1002/osp4.312. | Intervention/exposure
60 | Ash, DM, Tatala, SR, Frongillo, EA, Jr, Ndossi, GD, Latham, MC. Randomized efficacy trial of a micronutrient-fortified beverage in primary school children in Tanzania. Am J Clin Nutr. 2003. 77:891-8. doi:10.1093/ajcn/77.4.891. | Country
61 | Ashley, JM, Herzog, H, Clodfelter, S, Bovee, V, Schrage, J, Pritsos, C. Nutrient adequacy during weight loss interventions: a randomized study in women comparing the dietary intake in a meal replacement group with a traditional food group. Nutr J. 2007. 6:12. doi:10.1186/1475-2891-6-12. | Intervention/exposure
62 | Ashley, JM, St Jeor, ST, Perumean-Chaney, S, Schrage, J, Bovee, V. Meal replacements in weight intervention. Obes Res. 2001. 9 Suppl 4:312s-320s. doi:10.1038/oby.2001.136. | Intervention/exposure
63 | Aslani, N, Entezari, MH, Maghsoudi, Z, Askari, G. Effect of garlic and lemon juice mixture on fasting blood sugar, diastolic and systolic blood pressure and body mass index in people with hyperlipidemia. Journal of isfahan medical school. 2015. 32:2491-2500. | Language
64 | Astrup, A. The role of protein and carbohydrates for weight loss and maintenance: evidence from the Diogenes study. Australasian medical journal.. 2011. 4:717. | Publication status
65 | Auvichayapat, P, Prapochanung, M, Tunkamnerdthai, O, Sripanidkulchai, BO, Auvichayapat, N, Thinkhamrop, B, Kunhasura, S, Wongpratoom, S, Sinawat, S, Hongprapas, P. Effectiveness of green tea on weight reduction in obese Thais: A randomized, controlled trial. Physiol Behav. 2008. 93:486-91. doi:10.1016/j.physbeh.2007.10.009. | Intervention/exposure
66 | Avalos, EE, Barrett-Connor, E, Kritz-Silverstein, D, Wingard, DL, Bergstrom, JN, Al-Delaimy, WK. Is dairy product consumption associated with the incidence of CHD?. Public Health Nutr. 2013. 16:2055-63. doi:10.1017/s1368980012004168. | Outcome
67 | Azadbakht, L, Nurbakhsh, S. Effect of soy drink replacement in a weight reducing diet on anthropometric values and blood pressure among overweight and obese female youths. Asia Pac J Clin Nutr. 2011. 20:383-9. | Comparator
68 | Azzini, E, Venneria, E, Ciarapica, D, Foddai, MS, Intorre, F, Zaccaria, M, Maiani, F, Palomba, L, Barnaba, L, Tubili, C, Maiani, G, Polito, A. Effect of Red Orange Juice Consumption on Body Composition and Nutritional Status in Overweight/Obese Female: A Pilot Study. Oxid Med Cell Longev. 2017. 2017:1672567. doi:10.1155/2017/1672567. | Study design
69 | Babault, N, Delay, G, Rodriguez, B, Guerin-Deremaux, L, Allaert, FA. Muscle mass and muscular strength impact of a supplementation with nutralys pea proteins or whey proteins in volunteers participating in physical training. Annals of nutrition and metabolism.. 2013. 63:521. doi:10.1159/000354245. | Publication status
70 | Baer, DJ, Stote, KS, Paul, DR, Harris, GK, Rumpler, WV, Clevidence, BA. Whey protein but not soy protein supplementation alters body weight and composition in free-living overweight and obese adults. J Nutr. 2011. 141:1489-94. doi:10.3945/jn.111.139840. | Comparator
71 | Bakuradze, T, Tausend, A, Galan, J, Maria Groh, IA, Berry, D, Tur, JA, Marko, D, Richling, E. Antioxidative activity and health benefits of anthocyanin-rich fruit juice in healthy volunteers. Free Radic Res. 2019. 1-11. doi:10.1080/10715762.2019.1618851. | Comparator
72 | Balk, L, Hoekstra, T, Twisk, J. Relationship between long-term coffee consumption and components of the metabolic syndrome: The Amsterdam growth and health longitudinal study. European Journal of Epidemiology. 2009. 24:203-209. doi:10.1007/s10654-009-9323-1. | Intervention/exposure
73 | Balsan, G, Pellanda, LC, Sausen, G, Galarraga, T, Zaffari, D, Pontin, B, Portal, VL. Effect of yerba mate and green tea on paraoxonase and leptin levels in patients affected by overweight or obesity and dyslipidemia: a randomized clinical trial. Nutr J. 2019. 18:5. doi:10.1186/s12937-018-0426-y. | Outcome
74 | Banuls, C, Rovira-Llopis, S, Lopez-Domenech, S, Veses, S, Victor, VM, Rocha, M, Hernandez-Mijares, A. Effect of consumption of a carob pod inositol-enriched beverage on insulin sensitivity and inflammation in middle-aged prediabetic subjects. Food Funct. 2016. 7:4379-4387. doi:10.1039/c6fo01021k. | Comparator
75 | Banzer, W, Berg, A, Braumann, K, Fuhrer-Sakel, D, Halle, M, Martin, S, McCarthy, D, Predel, GH, Scholze, J, Seyller, C, etal, . Benefits of the ACOORH concept on weight control and metabolic regulation after 12 weeks of intervention: results of a multicenter RCT. Obesity facts. 2018. 11:313-. doi:10.1159/000489691. | Publication status
76 | Banzer, W, Berg, A, Braumann, K, Fuhrer-Sakel, D, Halle, M, Martin, S, McCarthy, D, Predel, GH, Scholze, J, Seyller, C, etal, . Improvement of prediabetic condition after 4 and 12 weeks intervention by the ACOORH concept-subanalysis of a multicenter RCT. Obesity facts. 2018. 11:293-. doi:10.1159/000489691. | Publication status
77 | Barba, G, Troiano, E, Russo, P, Venezia, A, Siani, A. Inverse association between body mass and frequency of milk consumption in children. Br J Nutr. 2005. 93:15-9. | Study design
78 | Barebring, L, Brembeck, P, Lof, M, Brekke, HK, Winkvist, A, Augustin, H. Food intake and gestational weight gain in Swedish women. Springerplus. 2016. 5:377. doi:10.1186/s40064-016-2015-x. | Study design
79 | Baron, KG, Reid, KJ, Kern, AS, Zee, PC. Role of sleep timing in caloric intake and BMI. Obesity (Silver Spring). 2011. 19:1374-81. doi:10.1038/oby.2011.100. | Study design; Intervention/exposure
80 | Barquera, S, Espinosa, J, Monterrubio, E, Rivera, J. Physical well-being associated to water consumption in adults. Obesity reviews. 2014. 15:156. doi:10.1111/obr.12151. | Publication status
81 | Barrington, WE, Beresford, SAA. Applying Multiple Statistical Methods to Derive an Index of Dietary Behaviors Most Related to Obesity. Am J Epidemiol. 2018. 187:1559-1569. doi:10.1093/aje/kwx370. | Intervention/exposure
82 | Basu, A, Betts, NM, Mulugeta, A, Tong, C, Newman, E, Lyons, TJ. Green tea supplementation increases glutathione and plasma antioxidant capacity in adults with the metabolic syndrome. Nutr Res. 2013. 33:180-7. doi:10.1016/j.nutres.2012.12.010. | Other (e.g., duplicative data)
83 | Basu, A, Betts, NM, Ortiz, J, Simmons, B, Wu, M, Lyons, TJ. Low-energy cranberry juice decreases lipid oxidation and increases plasma antioxidant capacity in women with metabolic syndrome. Nutrition Research. 2011. 31:190-196. doi:10.1016/j.nutres.2011.02.003. | Comparator
84 | Basu, A, Du, M, Sanchez, K, Leyva, MJ, Betts, NM, Blevins, S, Wu, M, Aston, CE, Lyons, TJ. Green tea minimally affects biomarkers of inflammation in obese subjects with metabolic syndrome. Nutrition. 2011. 27:206-13. doi:10.1016/j.nut.2010.01.015. | Other (e.g., duplicative data)
85 | Basu, A, Sanchez, K, Leyva, MJ, Wu, M, Betts, NM, Aston, CE, Lyons, TJ. Green tea supplementation affects body weight, lipids, and lipid peroxidation in obese subjects with metabolic syndrome. J Am Coll Nutr. 2010. 29:31-40. | Intervention/exposure
86 | Bauer, JM, Verlaan, S, Sieber, CC, Cederholm, T. Effects of a high whey, leucine-enriched nutritional supplement on muscle mass, strength, and function in non-malnourished elderly with low physical function: a double blind, randomised controlled clinical trial. Clinical nutrition.. 2014. 33:S10. | Publication status
87 | Baxter, SD, Paxton-Aiken, AE, Tebbs, JM, Royer, JA, Guinn, CH, Finney, CJ. Secondary analyses of data from 4 studies with fourth-grade children show that sex, race, amounts eaten of standardized portions, and energy content given in trades explain the positive relationship between body mass index and energy intake at school-provided meals. Nutr Res. 2012. 32:659-68. doi:10.1016/j.nutres.2012.07.001. | Study design
88 | Bayer, O, von Kries, R, Strauss, A, Mitschek, C, Toschke, AM, Hose, A, Koletzko, BV. Short- and mid-term effects of a setting based prevention program to reduce obesity risk factors in children: a cluster-randomized trial. Clin Nutr. 2009. 28:122-8. doi:10.1016/j.clnu.2009.01.001. | Intervention/exposure
89 | Bays, H, Frestedt, JL, Bell, M, Williams, C, Kolberg, L, Schmelzer, W, Anderson, JW. Reduced viscosity Barley beta-Glucan versus placebo: a randomized controlled trial of the effects on insulin sensitivity for individuals at risk for diabetes mellitus. Nutr Metab (Lond). 2011. 8:58. doi:10.1186/1743-7075-8-58. | Intervention/exposure; Duplicate
90 | Bays, H, Frestedt, JL, Bell, M, Williams, C, Kolberg, L, Schmelzer, W, Anderson, JW. Reduced viscosity Barley - Glucan versus placebo: A randomized controlled trial of the effects on insulin sensitivity for individuals at risk for diabetes mellitus. Nutrition and Metabolism. 2011. 8. doi:10.1186/1743-7075-8-58. | Intervention/exposure; Comparator
91 | Beaglehole, R. Sugar sweetened beverages, obesity, diabetes and oral health: a preventable crisis. Pac Health Dialog. 2014. 20:39-42. | Study design
92 | Beavers, KM, Gordon, MM, Easter, L, Beavers, DP, Hairston, KG, Nicklas, BJ, Vitolins, MZ. Effect of protein source during weight loss on body composition, cardiometabolic risk and physical performance in abdominally obese, older adults: a pilot feeding study. J Nutr Health Aging. 2015. 19:87-95. doi:10.1007/s12603-015-0438-7. | Intervention/exposure
93 | Beavers, KM, Gordon, MM, Easter, L, Beavers, DP, Hairston, KG, Nicklas, BJ, Vitolins, MZ. Effect of protein source during weight loss on body composition, cardiometabolic risk and physical performance in abdominally obese, older adults: A pilot feeding study. Journal of Nutrition, Health and Aging. 2014. 19:87-95. doi:10.1007/s12603-015-0438-7. | Intervention/exposure
94 | Beck, TW, Housh, TJ, Johnson, GO, Coburn, JW, Malek, MH, Cramer, JT. Effects of a drink containing creatine, amino acids, and protein combined with ten weeks of resistance training on body composition, strength, and anaerobic performance. J Strength Cond Res. 2007. 21:100-4. doi:10.1519/r-18685.1. | Intervention/exposure; Comparator
95 | Bell, KE, Snijders, T, Zulyniak, M, Kumbhare, D, Parise, G, Chabowski, A, Phillips, SM. A whey protein-based multi-ingredient nutritional supplement stimulates gains in lean body mass and strength in healthy older men: A randomized controlled trial. PLoS One. 2017. 12:e0181387. doi:10.1371/journal.pone.0181387. | Intervention/exposure; Comparator
96 | Bellisle, F, Rolland-Cachera, MF. Three consecutive (1993, 1995, 1997) surveys of food intake, nutritional attitudes and knowledge, and lifestyle in 1000 French children, aged 9-11 years. J Hum Nutr Diet. 2007. 20:241-51. doi:10.1111/j.1365-277X.2007.00773.x. | Study design; Intervention/exposure
97 | Bello, JK, Stulberg, DB, Zhou, Y, Wang, C. Physical Activity and Consumption Patterns of Reproductive-Aged Women by BMI Category. Matern Child Health J. 2018. 22:713-724. doi:10.1007/s10995-018-2440-2. | Study design
98 | Bendtsen, LQ, Lorenzen, JK, Larsen, TM, van Baak, M, Papadaki, A, Martinez, JA, Handjieva-Darlenska, T, Jebb, SA, Kunešová, M, Pfeiffer, AF, etal, . Associations between dairy protein intake and body weight and risk markers of diabetes and CVD during weight maintenance. British journal of nutrition. 2014. 111:944-953. doi:10.1017/S0007114513003322. | Intervention/exposure
99 | Benito, P, Caballero, J, Moreno, J, Gutiérrez-Alcántara, C, Muñoz, C, Rojo, G, Garcia, S, Soriguer, FC. Effects of milk enriched with ω-3 fatty acid, oleic acid and folic acid in patients with metabolic syndrome. Clinical Nutrition. 2006. 25:581-587. doi:10.1016/j.clnu.2005.12.006. | Comparator
100 | Berg, A, Frey, I, Deibert, P, Landmann, U, Konig, D, Schmidt-Trucksass, A, Rucker, G, Kreiter, H, Berg, A, Dickhuth, HH. Weight reduction is feasible - Preliminary results of a controlled, randomised intervention study in overweight adults. Ernahrungs umschau. 2003. 50:386-393+374. | Language
101 | Berg, A, Koohkan, S, Banzer, W, Braumann, KM, Führer-Sakel, D, Halle, M, Martin, S, Predel, HG, Toplak, H. The almased concept against overweight and obesity and related health risk (ACOORH)-first results of an interim analysis. Diabetes technology & therapeutics. 2016. 18:A131-A132. doi:10.1089/dia.2016.2525. | Publication status
102 | Berg, A, Koohkan, S, Halle, M, Martin, S, Predel, H, Toplak, H. The ACOORH concept against overweight and obesity and related health risk-results on weight control and metabolic regulation after 12 weeks of intervention. Obesity facts. Conference: european obesity summit (EOS): 1st joint congress of EASO and IFSO-EC. Gothenburg sweden. Conference start: 20160601. Conference end: 20160604. Conference publication: (var.pagings). 2016. 9:259. doi:10.1159/000446744. | Publication status
103 | Berger, PK, Principe, JL, Laing, EM, Henley, EC, Pollock, NK, Taylor, RG, Blair, RM, Baile, CA, Hall, DB, Lewis, RD. Weight gain in college females is not prevented by isoflavone-rich soy protein: a randomized controlled trial. Nutr Res. 2014. 34:66-73. doi:10.1016/j.nutres.2013.09.005. | Comparator
104 | Bergholdt, HK, Nordestgaard, BG, Ellervik, C. Milk intake is not associated with low risk of diabetes or overweight-obesity: a Mendelian randomization study in 97,811 Danish individuals. Am J Clin Nutr. 2015. 102:487-96. doi:10.3945/ajcn.114.105049. | Study design
105 | Berkey, CS, Rockett, HR, Colditz, GA. Weight gain in older adolescent females: the internet, sleep, coffee, and alcohol. J Pediatr. 2008. 153:635-9, 639.e1. doi:10.1016/j.jpeds.2008.04.072. | Study design
106 | Berkowitz, RI, Wadden, TA, Gehrman, CA, Bishop-Gilyard, CT, Moore, RH, Womble, LG, Cronquist, JL, Trumpikas, NL, Levitt Katz, LE, Xanthopoulos, MS. Meal replacements in the treatment of adolescent obesity: a randomized controlled trial. Obesity (Silver Spring). 2011. 19:1193-9. doi:10.1038/oby.2010.288. | Intervention/exposure
107 | Berthold, HK, Schulte, DM, Lapointe, JF, Lemieux, P, Krone, W, Gouni-Berthold, I. The whey fermentation product malleable protein matrix decreases triglyceride concentrations in subjects with hypercholesterolemia: A randomized placebo-controlled trial1. Journal of Dairy Science. 2011. 94:589-601. doi:10.3168/jds.2010-3115. | Comparator; Outcome
108 | Bes-Rastrollo, M, Sanchez-Villegas, A, Gomez-Gracia, E, Martinez, JA, Pajares, RM, Martinez-Gonzalez, MA. Predictors of weight gain in a Mediterranean cohort: the Seguimiento Universidad de Navarra Study 1. Am J Clin Nutr. 2006. 83:362-70; quiz 394-5. doi:10.1093/ajcn/83.2.362. | Publication date
109 | Bes-Rastrollo, M, Sánchez-Villegas, A, Gómez-Gracia, E, Martínez, JA, Pajares, RM, Martínez-González, MA. Predictors of weight gain in a Mediterranean cohort: The Seguimiento Universidad de Navarra Study. American Journal of Clinical Nutrition. 2006. 83:362-370. | Duplicate
110 | Bhupathiraju, SN, Pan, A, Manson, JE, Willett, WC, van Dam, RM, Hu, FB. Changes in coffee intake and subsequent risk of type 2 diabetes: three large cohorts of US men and women. Diabetologia. 2014. 57:1346-54. doi:10.1007/s00125-014-3235-7. | Outcome
111 | Biddle, MJ, Lennie, TA, Mudd-Martin, G, Bailey, A, Novak, MJ, Casey, B, Chung, M, Moser, D. A dietary intervention rich in antioxidants reduces inflammation and oxidative stress. Circulation. 2013. 128. | Publication status
112 | Bidel, S, Hu, G, Jousilahti, P, Antikainen, R, Pukkala, E, Hakulinen, T, Tuomilehto, J. Coffee consumption and risk of colorectal cancer. European Journal of Clinical Nutrition. 2010. 64:917-923. doi:10.1038/ejcn.2010.103. | Outcome
113 | Bigornia, SJ, LaValley, MP, Moore, LL, Northstone, K, Emmett, P, Ness, AR, Newby, PK. Dairy intakes at age 10 years do not adversely affect risk of excess adiposity at 13 years. J Nutr. 2014. 144:1081-90. doi:10.3945/jn.113.183640. | Intervention/exposure
114 | Bihuniak, J, Kerstetter, J, Brindisi, J, Sullivan, R, Mangano, K, Larocque, S, Kotler, B, Simpson, C, Cusano, AM, Kleppinger, A, etal, . The effect of long-term whey protein supplementation on bone mineral density and body composition in older adults: a randomized, double-blind, controlled trial. Endocrine reviews. Conference: 96th annual meeting and expo of the endocrine society, ENDO 2014. Chicago, IL united states. Conference start: 20140621. Conference end: 20140624. Conference publication: (var.pagings). 2014. 35. | Publication status
115 | Bilgi, P, Ersoy, G, Ergun, N, Hongu, N. The effects of whey protein supplementation on body composition and physical performance tests in men. FASEB journal. 2014. 28. | Publication status
116 | Bird, SP, Tarpenning, KM, Marino, FE. Independent and combined effects of liquid carbohydrate/essential amino acid ingestion on hormonal and muscular adaptations following resistance training in untrained men. Eur J Appl Physiol. 2006. 97:225-38. doi:10.1007/s00421-005-0127-z. | Intervention/exposure
117 | Biver, E, Durosier-Izart, C, Merminod, F, Chevalley, T, van Rietbergen, B, Ferrari, SL, Rizzoli, R. Fermented dairy products consumption is associated with attenuated cortical bone loss independently of total calcium, protein, and energy intakes in healthy postmenopausal women. Osteoporos Int. 2018. 29:1771-1782. doi:10.1007/s00198-018-4535-4. | Intervention/exposure; Outcome
118 | Bjelland, M, Bergh, IH, Grydeland, M, Klepp, KI, Andersen, LF, Anderssen, SA, Ommundsen, Y, Lien, N. Changes in adolescents’ intake of sugar-sweetened beverages and sedentary behaviour: Results at 8 month mid-way assessment of the HEIA study - a comprehensive, multi-component school-based randomized trial. International Journal of Behavioral Nutrition and Physical Activity. 2011. 8. doi:10.1186/1479-5868-8-63. | Intervention/exposure
119 | Bjelland, M, Hausken, SES, Bergh, IH, Grydeland, M, Klepp, KI, Andersen, LF, Totland, TH, Lien, N. Changes in adolescents’ and parents’ intakes of sugar-sweetened beverages, fruit and vegetables after 20 months: Results from the HEIA study - A comprehensive, multi-component school-based randomized trial. Food and Nutrition Research. 2015. 59. doi:10.3402/fnr.v59.25932. | Intervention/exposure; Outcome
120 | Blanco-Rojo, R, Perez-Granados, AM, Toxqui, L, Gonzalez-Vizcayno, C, Delgado, MA, Vaquero, MP. Efficacy of a microencapsulated iron pyrophosphate-fortified fruit juice: a randomised, double-blind, placebo-controlled study in Spanish iron-deficient women. Br J Nutr. 2011. 105:1652-9. doi:10.1017/s0007114510005490. | Comparator
121 | Blumenfeld Olivares, JA, San Mauro Martín, I, Calle, ME, Bischofberger Valdés, C, Perez Arruche, E, Arce Delgado, E, Ciudad, MJ, Hernández Cabría, M, Collado Yurita, L. LOW-FAT, FERMENTED MILK ENRICHED WITH PLANT STEROLS, A STRATEGY TO REDUCE HYPERTRIGLYCERIDEMA IN CHILDREN, A DOUBLE-BLIND, RANDOMIZED PLACEBO-COTROLLED TRIAL. Nutricion hospitalaria. 2015. 32:1056-1060. doi:10.3305/nh.2015.32.3.9319. | Language
122 | Bohl, M, Bjornshave, A, Larsen, MK, Gregersen, S, Hermansen, K. Effects of medium-chain saturated dairy fat on the body composition of abdominal obese subjects (DairyHealth): a 12-week, randomised, double-blinded, intervention study. Diabetologia. 2015. 58:S335-S336. doi:10.1007/s00125-015-3687-4. | Publication status
123 | Bohl, M, Bjornshave, A, Larsen, MK, Gregersen, S, Hermansen, K. The effects of proteins and medium-chain fatty acids from milk on body composition, insulin sensitivity and blood pressure in abdominally obese adults. Eur J Clin Nutr. 2017. 71:76-82. doi:10.1038/ejcn.2016.207. | Intervention/exposure
124 | Bohl, M, Bjornshave, A, Rasmussen, KV, Schioldan, AG, Amer, B, Larsen, MK, Dalsgaard, TK, Holst, JJ, Herrmann, A, O’Neill, S, O’Driscoll, L, Afman, L, Jensen, E, Christensen, MM, Gregersen, S, Hermansen, K. Dairy proteins, dairy lipids, and postprandial lipemia in persons with abdominal obesity (DairyHealth): a 12-wk, randomized, parallel-controlled, double-blinded, diet intervention study. Am J Clin Nutr. 2015. 101:870-8. doi:10.3945/ajcn.114.097923. | Intervention/exposure
125 | Bohn, SK, Croft, KD, Burrows, S, Puddey, IB, Mulder, TP, Fuchs, D, Woodman, RJ, Hodgson, JM. Effects of black tea on body composition and metabolic outcomes related to cardiovascular disease risk: a randomized controlled trial. Food Funct. 2014. 5:1613-20. doi:10.1039/c4fo00209a. | Comparator
126 | Bonet Serra, B, Quintanar Rioja, A, Viana Arribas, M, Iglesias-Gutierrez, E, Varela-Moreiras, G. The effects of yogurt with isomer enriched conjugated linoleic acid on insulin resistance in obese adolescents. Revista espanola de pediatria. 2008. 64:94-100. | Language
127 | Boonchoo, W, Takemi, Y, Hayashi, F, Koiwai, K, Ogata, H. Dietary intake and weight status of urban Thai preadolescents in the context of food environment. Prev Med Rep. 2017. 8:153-157. doi:10.1016/j.pmedr.2017.09.009. | Study design
128 | Boonyavarakul, A, Leelawattana, R, Pongchaiyakul, C, Buranapin, S, Phanachet, P, Pramyothin, P. Effects of meal replacement therapy on metabolic outcomes in Thai patients with type 2 diabetes: A randomized controlled trial. Nutr Health. 2018. 260106018800074. doi:10.1177/0260106018800074. | Health status
129 | Bortolotti, M, Maiolo, E, Corazza, M, Van Dijke, E, Schneiter, P, Boss, A, Carrel, G, Giusti, V, Le, KA, Quo Chong, DG, Buehler, T, Kreis, R, Boesch, C, Tappy, L. Effects of a whey protein supplementation on intrahepatocellular lipids in obese female patients. Clin Nutr. 2011. 30:494-8. doi:10.1016/j.clnu.2011.01.006. | Intervention/exposure; Health status
130 | Bossingham, MJ, Carnell, NS, Campbell, WW. Water balance, hydration status, and fat-free mass hydration in younger and older adults. Am J Clin Nutr. 2005. 81:1342-50. doi:10.1093/ajcn/81.6.1342. | Intervention/exposure; Comparator
131 | Bowen, J, Brindal, E, James-Martin, G, Noakes, M. Randomized Trial of a High Protein, Partial Meal Replacement Program with or without Alternate Day Fasting: Similar Effects on Weight Loss, Retention Status, Nutritional, Metabolic, and Behavioral Outcomes. Nutrients. 2018. 10. doi:10.3390/nu10091145. | Intervention/exposure
132 | Bralic, I, Kovacic, V. Social and behavioural determinants of body mass index among adolescent females in Croatia. Public Health. 2005. 119:189-191. doi:10.1016/j.puhe.2004.04.005. | Study design
133 | Bravo, S, Lowndes, J, Sinnett, S, Yu, Z, Rippe, J. Consumption of sucrose and high-fructose corn syrup does not increase liver fat or ectopic fat deposition in muscles. Appl Physiol Nutr Metab. 2013. 38:681-8. doi:10.1139/apnm-2012-0322. | Comparator
134 | Bremer, AA, Lustig, RH. Effects of sugar-sweetened beverages on children. Pediatr Ann. 2012. 41:26-30. doi:10.3928/00904481-20111209-09. | Study design
135 | Briganti, S, Zelaschi, R, Ermetici, F, Capitanio, G, Romeo, G, Cancellato, A, Morricone, L, Malavazos, AE. The Italian E.A.T. Project: effectiveness of a multicomponent school-based health promotion study on measures of fatness and behavior in teenagers. Eating and weight disorders. 2014. 19:444-445. doi:10.1007/s40519-014-0134-3. | Publication status
136 | Brikou, D, Zannidi, D, Karfopoulou, E, Anastasiou, CA, Yannakoulia, M. Breakfast consumption and weight-loss maintenance: results from the MedWeight study. Br J Nutr. 2016. 115:2246-51. doi:10.1017/s0007114516001550. | Study design; Intervention/exposure
137 | Brinkworth, GD, Buckley, JD, Slavotinek, JP, Kurmis, AP. Effect of bovine colostrum supplementation on the composition of resistance trained and untrained limbs in healthy young men. Eur J Appl Physiol. 2004. 91:53-60. doi:10.1007/s00421-003-0944-x. | Intervention/exposure; Comparator
138 | Brito Beck da Silva, K, Ortelan, N, Giardini Murta, S, Sartori, I, Couto, RD, Leovigildo Fiaccone, R, Lima Barreto, M, Jones Bell, M, Barr Taylor, C, Ribeiro-Silva, RC. Evaluation of the Computer-Based Intervention Program Stayingfit Brazil to Promote Healthy Eating Habits: The Results from a School Cluster-Randomized Controlled Trial. Int J Environ Res Public Health. 2019. 16. doi:10.3390/ijerph16101674. | Intervention/exposure
139 | Brunkwall, L, Chen, Y, Hindy, G, Rukh, G, Ericson, U, Barroso, I, Johansson, I, Franks, PW, Orho-Melander, M, Renstrom, F. Sugar-sweetened beverage consumption and genetic predisposition to obesity in 2 Swedish cohorts. Am J Clin Nutr. 2016. 104:809-15. doi:10.3945/ajcn.115.126052. | Study design
140 | Bruun, JM, Maersk, M, Belza, A, Astrup, A, Richelsen, B. Consumption of sucrose-sweetened soft drinks increases plasma levels of uric acid in overweight and obese subjects: a 6-month randomised controlled trial. Eur J Clin Nutr. 2015. 69:949-53. doi:10.1038/ejcn.2015.95. | Other (e.g., duplicative data)
141 | Burke, DG, Chilibeck, PD, Davidson, KS, Candow, DG, Farthing, J, Smith-Palmer, T. The effect of whey protein supplementation with and without creatine monohydrate combined with resistance training on lean tissue mass and muscle strength. Int J Sport Nutr Exerc Metab. 2001. 11:349-64. | Intervention/exposure; Comparator
142 | Buscemi, S, Rosafio, G, Arcoleo, G, Mattina, A, Canino, B, Montana, M, Verga, S, Rini, G. Effects of red orange juice intake on endothelial function and inflammatory markers in adult subjects with increased cardiovascular risk. Am J Clin Nutr. 2012. 95:1089-95. doi:10.3945/ajcn.111.031088. | Comparator
143 | Busnello, FM, Bodanese, LC, Pellanda, LC, Santos, ZE. Nutritional intervention and the impact on adherence to treatment in patients with metabolic syndrome. Arq Bras Cardiol. 2011. 97:217-24. doi:10.1590/s0066-782x2011005000077. | Intervention/exposure
144 | Byrne, R, Zhou, Y, Perry, R, Mauch, C, Magarey, A. Beverage intake of Australian children and relationship with intake of fruit, vegetables, milk and body weight at 2, 3.7 and 5 years of age. Nutr Diet. 2018. 75:159-166. doi:10.1111/1747-0080.12409. | Study design
145 | Cameron, AJ, van Stralen, MM, Brug, J, Salmon, J, Bere, E, Chinapaw, MJ, De Bourdeaudhuij, I, Jan, N, Manios, Y, Moreno, LA, Velde, SJ. Television in the bedroom and increased body weight: potential explanations for their relationship among European schoolchildren. Pediatr Obes. 2013. 8:130-41. doi:10.1111/j.2047-6310.2012.00094.x. | Study design
146 | Campbell, WW, Kim, JE, Amankwaah, AF, Gordon, SL, Weinheimer-Haus, EM. Higher Total Protein Intake and Change in Total Protein Intake Affect Body Composition but Not Metabolic Syndrome Indexes in Middle-Aged Overweight and Obese Adults Who Perform Resistance and Aerobic Exercise for 36 Weeks. J Nutr. 2015. 145:2076-83. doi:10.3945/jn.115.213595. | Intervention/exposure
147 | Campos, V, Despland, C, Brandejsky, V, Kreis, R, Schneiter, P, Boesch, C, Tappy, L. Metabolic Effects of Replacing Sugar-Sweetened Beverages with Artificially-Sweetened Beverages in Overweight Subjects with or without Hepatic Steatosis: A Randomized Control Clinical Trial. Nutrients. 2017. 9. doi:10.3390/nu9030202. | Publication status
148 | Campos, V, Despland, C, Kreis, R, Schneiter, P, Boesch, C, Tappy, L. Metabolic effects of replacing sugar-sweetened by artifcially sweetened beverages in overweight subjects with or without hepatic steatosis: a randomized control clinical trial. Obesity facts. 2017. 10:190-191. doi:10.1159/000468958. | Publication status
149 | Campos, V, Despland, C, Schneiter, Ph, Brandejsky, V, Kreis, R, Boesch, Ch, Tappy, L. A randomized control trial of sugar-sweetened and artificially sweetened beverages and intrahepatic fat in overweight subjects. FASEB journal. 2015. 29. | Publication status
150 | Canas, JA, Damaso, L, Altomare, A, Hossain, J, Balagopal, B. Effect of a fruit and vegetable juice concentrate (FVJC) Vs. medical nutrition therapy alone on metabolic syndrome components in obese children: a 6 month pilot double blind placebo-controlled study. FASEB journal. 2011. 25. | Publication status
151 | Canfi, A, Gepner, Y, Schwarzfuchs, D, Golan, R, Shahar, DR, Fraser, D, Witkow, S, Greenberg, I, Sarusi, B, Vardi, H, Friger, M, Stampfer, MJ, Shai, I. Effect of changes in the intake of weight of specific food groups on successful body weight loss during a multi-dietary strategy intervention trial. J Am Coll Nutr. 2011. 30:491-501. | Intervention/exposure
152 | Capomolla, AS, Janda, E, Paone, S, Parafati, M, Sawicki, T, Mollace, R, Ragusa, S, Mollace, V. Atherogenic Index Reduction and Weight Loss in Metabolic Syndrome Patients Treated with A Novel Pectin-Enriched Formulation of Bergamot Polyphenols. Nutrients. 2019. 11. doi:10.3390/nu11061271. | Intervention/exposure
153 | Cardile, V, Graziano, AC, Venditti, A. Clinical evaluation of Moro (Citrus sinensis (L.) Osbeck) orange juice supplementation for the weight management. Nat Prod Res. 2015. 29:2256-60. doi:10.1080/14786419.2014.1000897. | Intervention/exposure
154 | Cardon, G, De Bourdeaudhuij, I, Iotova, V, Latomme, J, Socha, P, Koletzko, B, Moreno, L, Manios, Y, Androutsos, O, De Craemer, M. Health Related Behaviours in Normal Weight and Overweight Preschoolers of a Large Pan-European Sample: The ToyBox-Study. PLoS One. 2016. 11:e0150580. doi:10.1371/journal.pone.0150580. | Study design
155 | Cardoso, GA, Salgado, JM, Cesar Mde, C, Donado-Pestana, CM. The effects of green tea consumption and resistance training on body composition and resting metabolic rate in overweight or obese women. J Med Food. 2013. 16:120-7. doi:10.1089/jmf.2012.0062. | Comparator
156 | Carwile, JL, Willett, WC, Spiegelman, D, Hertzmark, E, Rich-Edwards, J, Frazier, AL, Michels, KB. Sugar-sweetened beverage consumption and age at menarche in a prospective study of US girls. Hum Reprod. 2015. 30:675-83. doi:10.1093/humrep/deu349. | Outcome
157 | Cerini, C, Mameli, C, Zuccotti, GV. Soft drinks and obesity in children: an intricate puzzle. Expert Rev Endocrinol Metab. 2013. 8:5-7. doi:10.1586/eem.12.70. | Study design
158 | Cervo, MMC, Mendoza, DS, Barrios, EB, Panlasigui, LN. Effects of Nutrient-Fortified Milk-Based Formula on the Nutritional Status and Psychomotor Skills of Preschool Children. J Nutr Metab. 2017. 2017:6456738. doi:10.1155/2017/6456738. | Comparator; Country
159 | Cetin, I, Nalbantcilar, MT, Tosun, K, Nazik, A. Erratum to: How Trace Element Levels of Public Drinking Water Affect Body Composition in Turkey. Biol Trace Elem Res. 2017. 178:170. doi:10.1007/s12011-017-1026-y. | Study design
160 | Cetin, I, Nalbantcilar, MT, Tosun, K, Nazik, A. How Trace Element Levels of Public Drinking Water Affect Body Composition in Turkey. Biol Trace Elem Res. 2017. 175:263-270. doi:10.1007/s12011-016-0779-z. | Study design; Intervention/exposure
161 | Chacko, E, McDuff, I, Jackson, R. Replacing sugar-based soft drinks with sugar-free alternatives could slow the progress of the obesity epidemic: have your Coke and drink it too. N Z Med J. 2003. 116:U649. | Study design
162 | Chai, SC, Davis, K, Wright, RS, Kuczmarski, MF, Zhang, Z, Lee, K, Luo, J. Tart cherry juice reduces systolic blood pressure in older adults. FASEB journal. 2017. 31. | Publication status
163 | Chai, SC, Davis, K, Wright, RS, Kuczmarski, MF, Zhang, Z. Impact of tart cherry juice on systolic blood pressure and low-density lipoprotein cholesterol in older adults: a randomized controlled trial. Food Funct. 2018. 9:3185-3194. doi:10.1039/c8fo00468d. | Comparator
164 | Chai, SC, Davis, K, Zhang, Z, Zha, L, Kirschner, KF. Effects of tart cherry juice on biomarkers of inflammation and oxidative stress in older adults. Nutrients. 2019. 11. doi:10.3390/nu11020228. | Other (e.g., duplicative data)
165 | Chaidez, V, McNiven, S, Vosti, SA, Kaiser, LL. Sweetened food purchases and indulgent feeding are associated with increased toddler anthropometry. J Nutr Educ Behav. 2014. 46:293-8. doi:10.1016/j.jneb.2013.05.011. | Population at Intervention/exposure
166 | Chaiyasoot, K, Sarasak, R, Pheungruang, B, Dawilai, S, Pramyothin, P, Boonyasiri, A, Supapueng, O, Jassil, FC, Yamwong, P, Batterham, RL. Evaluation of a 12-week lifestyle education intervention with or without partial meal replacement in Thai adults with obesity and metabolic syndrome: a randomised trial. Nutr Diabetes. 2018. 8:23. doi:10.1038/s41387-018-0034-0. | Intervention/exposure
167 | Chaloupka, FJ, Powell, LM, Chriqui, JF. Sugar-sweetened beverages and obesity: the potential impact of public policies. J Policy Anal Manage. 2011. 30:645-55. | Study design
168 | Chang, WC. Dietary intake and the risk of hyperuricemia, gout and chronic kidney disease in elderly Taiwanese men. Aging Male. 2011. 14:195-202. doi:10.3109/13685538.2010.512372. | Study design
169 | Chantre, P, Lairon, D. Recent findings of green tea extract AR25 (Exolise) and its activity for the treatment of obesity. Phytomedicine. 2002. 9:3-8. doi:10.1078/0944-7113-00078. | Intervention/exposure
170 | Chaves, G, Britez, N, Oviedo, G, Gonzalez, G, Italiano, C, Blanes, M, Sandoval, G, Mereles, D. Heavy drinkers of Ilex paraguariensis beverages show lower lipid profiles but higher body weight. Phytother Res. 2018. 32:1030-1038. doi:10.1002/ptr.6041. | Study design
171 | Chen, IJ, Liu, CY, Chiu, JP, Hsu, CH. Therapeutic effect of high-dose green tea extract on weight reduction: A randomized, double-blind, placebo-controlled clinical trial. Clin Nutr. 2016. 35:592-9. doi:10.1016/j.clnu.2015.05.003. | Intervention/exposure
172 | Chen, JL, Guedes, CM, Lung, AE. Smartphone-Based Healthy Weight Management Intervention for Chinese American Adolescents: short-Term Efficacy and Factors Associated With Decreased Weight. Journal of adolescent health. 2018. (no pagination). doi:10.1016/j.jadohealth.2018.08.022. | Intervention/exposure
173 | Chen, L, Appel, LJ, Loria, C, Lin, PH, Champagne, CM, Elmer, PJ, Ard, JD, Mitchell, D, Batch, BC, Svetkey, LP, Caballero, B. Reduction in consumption of sugar-sweetened beverages is associated with weight loss: the PREMIER trial. Am J Clin Nutr. 2009. 89:1299-306. doi:10.3945/ajcn.2008.27240. | Publication date
174 | Chen, L, Caballero, B, Mitchell, DC, Loria, C, Lin, PH, Champagne, CM, Elmer, PJ, Ard, JD, Batch, BC, Anderson, CA, Appel, LJ. Reducing consumption of sugar-sweetened beverages is associated with reduced blood pressure: a prospective study among United States adults. Circulation. 2010. 121:2398-406. doi:10.1161/circulationaha.109.911164. | Publication date
175 | Chen, SC, Lin, YH, Huang, HP, Hsu, WL, Houng, JY, Huang, CK. Effect of conjugated linoleic acid supplementation on weight loss and body fat composition in a Chinese population. Nutrition. 2012. 28:559-65. doi:10.1016/j.nut.2011.09.008. | Country
176 | Chen, W, Liu, Y, Yang, Q, Li, X, Yang, J, Wang, J, Shi, L, Chen, Y, Zhu, S. The Effect of Protein-Enriched Meal Replacement on Waist Circumference Reduction among Overweight and Obese Chinese with Hyperlipidemia. J Am Coll Nutr. 2016. 35:236-44. doi:10.1080/07315724.2014.989625. | Intervention/exposure
177 | Chen, Y, Xiang, J, Wang, Z, Xiao, Y, Zhang, D, Chen, X, Li, H, Liu, M, Zhang, Q. Associations of Bone Mineral Density with Lean Mass, Fat Mass, and Dietary Patterns in Postmenopausal Chinese Women: A 2-Year Prospective Study. PLoS One. 2015. 10:e0137097. doi:10.1371/journal.pone.0137097. | Intervention/exposure; Outcome
178 | Chen, Y, Zhang, Q, Wang, Y, Xiao, Y, Fu, R, Bao, H, Liu, M. Estimating the causal effect of milk powder supplementation on bone mineral density: a randomized controlled trial with both non-compliance and loss to follow-up. Eur J Clin Nutr. 2015. 69:824-30. doi:10.1038/ejcn.2015.3. | Intervention/exposure; Comparator
179 | Chew, B, Mathison, B, Kimble, L, McKay, D, Kaspar, K, Khoo, C, Chen, CO, Blumberg, J. Chronic consumption of a low calorie, high polyphenol cranberry beverage attenuates inflammation and improves glucoregulation and HDL cholesterol in healthy overweight humans: a randomized controlled trial. Eur J Nutr. 2019. 58:1223-1235. doi:10.1007/s00394-018-1643-z. | Outcome
180 | Chew, B, Mathison, B, Kimble, L, McKay, D, Kaspar, K, Khoo, C, Chen, Yo C, Blumberg, J. Chronic consumption of a low calorie, high polyphenol cranberry beverage attenuates inflammation and improves glucoregulation and HDL cholesterol in healthy overweight humans: a randomized controlled trial. European journal of nutrition. 2018. 1-13. doi:10.1007/s00394-018-1643-z. | Outcome
181 | Chiochetta, M, Ferreira, EJ, Moreira, ITDS, Avila, RCSD, Oliveira, AAD, Busnello, FM, Braganhol, E, Barschak, AG. Green Juice in Human Metabolism: A Randomized Trial. Journal of the American College of Nutrition. 2018. 37:670-676. doi:10.1080/07315724.2018.1457458. | Intervention/exposure; Comparator
182 | Choi, HJ, Joung, H, Lee, HJ, Jang, HB, Kang, JH, Song, J. The influence of dietary patterns on the nutritional profile in a korean child cohort study. Osong Public Health Res Perspect. 2011. 2:59-64. doi:10.1016/j.phrp.2011.04.007. | Study design; Intervention/exposure
183 | Choi, HK, Curhan, G. Soft drinks, fructose consumption, and the risk of gout in men: prospective cohort study. Bmj. 2008. 336:309-12. doi:10.1136/bmj.39449.819271.BE. | Outcome
184 | Choi, MK, Kim, MH. The Association between Coffee Consumption and Bone Status in Young Adult Males according to Calcium Intake Level. Clin Nutr Res. 2016. 5:180-9. doi:10.7762/cnr.2016.5.3.180. | Study design
185 | Christensen, L, Thorning, TK, Fabre, O, Legrand, R, Astrup, A, Hjorth, MF. Metabolic improvements during weight loss: The RNPC® cohort. Obesity Medicine. 2019. 14. doi:10.1016/j.obmed.2019.100085. | Study design; Intervention/exposure
186 | Christoforidis, A, Batzios, S, Sidiropoulos, H, Provatidou, M, Cassimos, D. The profile of the Greek ‘XXL’ family. Public Health Nutr. 2011. 14:1851-7. doi:10.1017/s1368980011000929. | Study design
187 | Chromiak, JA, Smedley, B, Carpenter, W, Brown, R, Koh, YS, Lamberth, JG, Joe, LA, Abadie, BR, Altorfer, G. Effect of a 10-week strength training program and recovery drink on body composition, muscular strength and endurance, and anaerobic power and capacity. Nutrition. 2004. 20:420-7. doi:10.1016/j.nut.2004.01.005. | Intervention/exposure; Comparator
188 | Chung, A, Peeters, A, Gearon, E, Backholer, K. Contribution of discretionary food and drink consumption to socio-economic inequalities in children’s weight: prospective study of Australian children. Int J Epidemiol. 2018. . doi:10.1093/ije/dyy020. | Intervention/exposure; Population at Intervention/exposure
189 | Claessens, M, van Baak, MA, Monsheimer, S, Saris, WH. The effect of a low-fat, high-protein or high-carbohydrate ad libitum diet on weight loss maintenance and metabolic risk factors. Int J Obes (Lond). 2009. 33:296-304. doi:10.1038/ijo.2008.278. | Intervention/exposure; Comparator
190 | Coburn, JW, Housh, DJ, Housh, TJ, Malek, MH, Beck, TW, Cramer, JT, Johnson, GO, Donlin, PE. Effects of leucine and whey protein supplementation during eight weeks of unilateral resistance training. J Strength Cond Res. 2006. 20:284-91. doi:10.1519/r-17925.1. | Intervention/exposure; Comparator
191 | Coelho, Rcla, Hermsdorff, HHM, Gomide, RS, Alves, RDM, Bressan, J. Orange juice with a high-fat meal prolongs postprandial lipemia in apparently healthy overweight/obese women. Arch Endocrinol Metab. 2017. 61:263-268. doi:10.1590/2359-3997000000229. | Outcome
192 | Coffee drinkers have a reduced risk of developing type 2 diabetes. Nature Clinical Practice Endocrinology and Metabolism. 2007. 3:200. doi:10.1038/ncpendmet0404. | Study design; Publication status
193 | Cohen, T, Hazell, T, Loiselle, SE, Kasvis, P, Vanstone, C, Kim, N, Plourde, H, Rodd, C, Weiler, H. A family-centered lifestyle intervention focused on milk and alternatives reduces adiposity in 6-to 8-year-old overweight and obese children compared to control: results at 6 months from a RCT. FASEB journal. 2014. 28. | Publication status
194 | Cohen, TR, Hazell, TJ, Loiselle, S, Kasvis, P, Vanstone, CA, Kim, N, Rodd, C, Weiler, HA. A family-centered lifestyle intervention focused on milk and alternatives reduces adiposity in six to eight Y old overweight and obese children compared to control: results at six months from a RCT. Paediatrics and child health (canada).. 2014. 19:e72. | Publication status; Duplicate
195 | Cohen, TR, Hazell, TJ, Vanstone, CA, Rodd, C, Weiler, HA. A family-centered lifestyle intervention for obese six- to eight-year-old children: Results from a one-year randomized controlled trial conducted in Montreal, Canada. Can J Public Health. 2016. 107:e453-e460. doi:10.17269/cjph.107.5470. | Intervention/exposure
196 | Cohen, TR, Hazell, TJ, Vanstone, CA, Rodd, C, Weiler, HA. Changes in eating behavior and plasma leptin in children with obesity participating in a family-centered lifestyle intervention. Appetite. 2018. 125:81-89. doi:10.1016/j.appet.2018.01.017. | Intervention/exposure; Outcome
197 | Cohen, TR, Hazell, TJ, Vanstone, CA, Rodd, C, Weiler, HA. Changes in lean mass and bone parameters in obese children participating in a familycentered lifestyle intervention: results from a 1-year RCT. FASEB journal. 2017. 31. | Publication status
198 | Coker, RH, Miller, S, Schutzler, S, Deutz, N, Wolfe, RR. Whey protein and essential amino acids promote the reduction of adipose tissue and increased muscle protein synthesis during caloric restriction-induced weight loss in elderly, obese individuals. Nutr J. 2012. 11:105. doi:10.1186/1475-2891-11-105. | Intervention/exposure; Comparator
199 | Coker, RH, Shin, K, Scholten, K, Johannsen, M, Tsigonis, J, Kim, IY, Schutzler, SE, Wolfe, RR. Essential amino acid-enriched meal replacement promotes superior net protein balance in older, overweight adults. Clinical Nutrition. 2019. . doi:10.1016/j.clnu.2018.12.013. | Intervention/exposure; Health status
200 | Colker, CM, Swain, MA, Fabrucini, B, Qiuhi, S, Kalman, DS. Effects of supplemental protein on body composition and muscular strength in healthy athletic male adults. Current Therapeutic Research - Clinical and Experimental. 2000. 61:19-28. doi:10.1016/S0011-393X(00)88492-1. | Intervention/exposure
201 | Colleran, HL, Lovelady, CA. Use of MyPyramid Menu Planner for Moms in a weight-loss intervention during lactation. J Acad Nutr Diet. 2012. 112:553-8. doi:10.1016/j.jand.2011.12.004. | Intervention/exposure
202 | Collin, LJ, Judd, S, Safford, M, Vaccarino, V, Welsh, JA. Association of Sugary Beverage Consumption With Mortality Risk in US Adults: A Secondary Analysis of Data From the REGARDS Study. JAMA Netw Open. 2019. 2:e193121. doi:10.1001/jamanetworkopen.2019.3121. | Outcome
203 | Collison, KS, Zaidi, MZ, Subhani, SN, Al-Rubeaan, K, Shoukri, M, Al-Mohanna, FA. Sugar-sweetened carbonated beverage consumption correlates with BMI, waist circumference, and poor dietary choices in school children. BMC Public Health. 2010. 10:234. doi:10.1186/1471-2458-10-234. | Study design
204 | Copperstone, C, McNeill, G, Aucott, L, Jackson, DM. A pilot study to improve sugar and water consumption in Maltese school children. Int J Adolesc Med Health. 2019. . doi:10.1515/ijamh-2018-0134. | Outcome
205 | Corella, D, Arregui, M, Coltell, O, Portolés, O, Guillem-Sáiz, P, Carrasco, P, Sorlí, JV, Ortega-Azorín, C, González, JI, Ordovás, JM. Association of the LCT-13910CT polymorphism with obesity and its modulation by dairy products in a mediterranean population. Obesity. 2011. 19:1707-1714. doi:10.1038/oby.2010.320. | Intervention/exposure
206 | Correction: Do Sugar-Sweetened Beverages Cause Obesity and Diabetes?. Ann Intern Med. 2017. 166:232. doi:10.7326/l16-0638. | Study design
207 | Cox, CL, Stanhope, KL, Schwarz, JM, Graham, JL, Hatcher, B, Griffen, SC, Bremer, AA, Berglund, L, McGahan, JP, Havel, PJ, Keim, NL. Consumption of fructose-sweetened beverages for 10 weeks reduces net fat oxidation and energy expenditure in overweight/obese men and women. Eur J Clin Nutr. 2012. 66:201-8. doi:10.1038/ejcn.2011.159. | Outcome; Other (e.g., duplicative data)
208 | Cox, CL, Stanhope, KL, Schwarz, JM, Graham, JL, Hatcher, B, Griffen, SC, Bremer, AA, Berglund, L, McGahan, JP, Keim, NL, Havel, PJ. Circulating concentrations of monocyte chemoattractant protein-1, plasminogen activator inhibitor-1, and soluble leukocyte adhesion molecule-1 in overweight/obese men and women consuming fructose- or glucose-sweetened beverages for 10 weeks. J Clin Endocrinol Metab. 2011. 96:E2034-8. doi:10.1210/jc.2011-1050. | Outcome
209 | Cox, CL, Stanhope, KL, Schwarz, JM, Graham, JL, Hatcher, B, Griffen, SC, Bremer, AA, Berglund, L, McGahan, JP, Keim, NL, Havel, PJ. Consumption of fructose- but not glucose-sweetened beverages for 10 weeks increases circulating concentrations of uric acid, retinol binding protein-4, and gamma-glutamyl transferase activity in overweight/obese humans. Nutr Metab (Lond). 2012. 9:68. doi:10.1186/1743-7075-9-68. | Outcome
210 | Cramer, JT, Housh, TJ, Johnson, GO, Coburn, JW, Stout, JR. Effects of a carbohydrate-, protein-, and ribose-containing repletion drink during 8 weeks of endurance training on aerobic capacity, endurance performance, and body composition. J Strength Cond Res. 2012. 26:2234-42. doi:10.1519/JSC.0b013e3182606cec. | Intervention/exposure
211 | Crawford, PB, Woodward-Lopez, G, Ritchie, L, Webb, K. How discretionary can we be with sweetened beverages for children?. J Am Diet Assoc. 2008. 108:1440-4. doi:10.1016/j.jada.2008.06.439. | Study design
212 | Creighton, S, Jay, M. Are non-nutritive sweetened beverages comparable to water in weight loss trials?. Journal of Clinical Outcomes Management. 2014. 21:490-492. | Study design
213 | Crézé, C, Notter-Bielser, ML, Knebel, JF, Campos, V, Tappy, L, Murray, M, Toepel, U. The impact of replacing sugar- by artificially-sweetened beverages on brain and behavioral responses to food viewing – An exploratory study. Appetite. 2018. 123:160-168. doi:10.1016/j.appet.2017.12.019. | Study design
214 | Cribb, PJ, Williams, AD, Stathis, CG, Carey, MF, Hayes, A. Effects of whey isolate, creatine, and resistance training on muscle hypertrophy. Med Sci Sports Exerc. 2007. 39:298-307. doi:10.1249/01.mss.0000247002.32589.ef. | Intervention/exposure; Comparator
215 | Crichton, GE, Alkerwi, A. Dairy food intake is positively associated with cardiovascular health: findings from Observation of Cardiovascular Risk Factors in Luxembourg study. Nutr Res. 2014. 34:1036-44. doi:10.1016/j.nutres.2014.04.002. | Study design
216 | Crichton, GE, Alkerwi, A. Whole-fat dairy food intake is inversely associated with obesity prevalence: findings from the Observation of Cardiovascular Risk Factors in Luxembourg study. Nutr Res. 2014. 34:936-43. doi:10.1016/j.nutres.2014.07.014. | Study design
217 | Crutchley, PW, Morenga, LT. Effect of sugar-sweetened soft drinks on serum uric acid and associated metabolic risk factors. FASEB journal. 2013. 27. | Publication status
218 | Cummings, DM, Henes, S, Kolasa, KM, Olsson, J, Collier, D. Insulin resistance status: predicting weight response in overweight children. Arch Pediatr Adolesc Med. 2008. 162:764-8. doi:10.1001/archpedi.162.8.764. | Outcome; Health status
219 | Cundiff, DK, Raghuvanshi, N. Future body mass index modelling based on macronutrient profiles and physical activity. Theor Biol Med Model. 2012. 9:43. doi:10.1186/1742-4682-9-43. | Study design; Intervention/exposure
220 | Cunha, D, Souza, B, Pereira, R, Sichieri, R. Preventing excessive weight gain by encouraging healthy eating habits among adolescents in Brazil: a randomised community trial. FASEB journal. 2012. 26. | Publication status
221 | Cunningham, E. What impact does water consumption have on weight loss or weight loss maintenance?. J Acad Nutr Diet. 2014. 114:2084. doi:10.1016/j.jand.2014.10.008. | Study design
222 | Cunningham, SA, Zavodny, M. Does the sale of sweetened beverages at school affect children’s weight?. Soc Sci Med. 2011. 73:1332-9. doi:10.1016/j.socscimed.2011.08.003. | Study design
223 | Daly, RM, Nowson, CA. Long-term effect of calcium-vitamin D3 fortified milk on blood pressure and serum lipid concentrations in healthy older men. European Journal of Clinical Nutrition. 2009. 63:993-1000. doi:10.1038/ejcn.2008.79. | Duplicate; Other (e.g., duplicative data)
224 | Davis, LM, Coleman, C, Kiel, J, Rampolla, J, Hutchisen, T, Ford, L, Andersen, WS, Hanlon-Mitola, A. Efficacy of a meal replacement diet plan compared to a food-based diet plan after a period of weight loss and weight maintenance: a randomized controlled trial. Nutr J. 2010. 9:11. doi:10.1186/1475-2891-9-11. | Intervention/exposure; Health status
225 | Davison, GW, McClean, C, Brown, J, Madigan, S, Gamble, D, Trinick, T, Duly, E. The effects of ingesting a carbohydrate-electrolyte beverage 15 minutes prior to high-intensity exercise performance. Research in Sports Medicine. 2008. 16:155-166. doi:10.1080/15438620802103155. | Intervention/exposure
226 | Davy, BM, Jahren, AH, Hedrick, VE, You, W, Zoellner, JM. Influence of an intervention targeting a reduction in sugary beverage intake on the delta13C sugar intake biomarker in a predominantly obese, health-disparate sample. Public Health Nutr. 2017. 20:25-29. doi:10.1017/s1368980016001439. | Intervention/exposure; Comparator
227 | Davy, BM, Jahren, AH, Hedrick, VE, You, W, Zoellner, JM. Influence of an intervention targeting a reduction in sugary beverage intake on the δ13C sugar intake biomarker in a predominantly obese, health-disparate sample. Public health nutrition. 2017. 20:25-29. doi:10.1017/S1368980016001439. | Comparator; Outcome
228 | de Branco, FMS, Carneiro, MAS, Rossato, LT, Nahas, PC, Teixeira, KRC, de Oliveira, GN, Jr, Orsatti, FL, de Oliveira, EP. Protein timing has no effect on lean mass, strength and functional capacity gains induced by resistance exercise in postmenopausal women: A randomized clinical trial. Clin Nutr. 2019. . doi:10.1016/j.clnu.2019.01.008. | Intervention/exposure
229 | De Giuseppe, R, Calcaterra, V, Biino, G, Manuelli, M, Mier, NR, Mantelli, M, De Filippo, M, Cossellu, G, Cena, H. Unhealthy lifestyle and oxidative damage in childhood obesity. Eat Weight Disord. 2018. . doi:10.1007/s40519-018-0626-7. | Study design
230 | de Koning, L, Malik, VS, Kellogg, MD, Rimm, EB, Willett, WC, Hu, FB. Sweetened beverage consumption, incident coronary heart disease, and biomarkers of risk in men. Circulation. 2012. 125:1735-41, s1. doi:10.1161/circulationaha.111.067017. | Outcome
231 | de Koning, L, Malik, VS, Rimm, EB, Willett, WC, Hu, FB. Sugar-sweetened and artificially sweetened beverage consumption and risk of type 2 diabetes in men. Am J Clin Nutr. 2011. 93:1321-7. doi:10.3945/ajcn.110.007922. | Outcome
232 | de Moraes, MM, Mediano, MFF, de Souza, RAG, Moura, AS, da Veiga, GV, Sichieri, R. Discouraging soft drink consumption reduces blood glucose and cholesterol of Brazilian elementary students: Secondary analysis of a randomized controlled trial. Prev Med. 2017. 100:223-228. doi:10.1016/j.ypmed.2017.04.035. | Intervention/exposure; Outcome
233 | de Ruyter, JC, Katan, MB, Kuijper, LD, Liem, DG, Olthof, MR. The effect of sugar-free versus sugar-sweetened beverages on satiety, liking and wanting: an 18 month randomized double-blind trial in children. PLoS One. 2013. 8:e78039. doi:10.1371/journal.pone.0078039. | Outcome
234 | De Ruyter, JC, Olthof, MO, Kuijper, LDJ, Liem, G, Seidell, JC, Katan, MB. Short-term satiety and long-term weight effects of sugarfree and sugar-sweetened beverages in children. Obesity facts.. 2013. 6:33. | Publication status
235 | de Silva-Sanigorski, AM, Bell, AC, Kremer, P, Nichols, M, Crellin, M, Smith, M, Sharp, S, de Groot, F, Carpenter, L, Boak, R, Robertson, N, Swinburn, BA. Reducing obesity in early childhood: results from Romp & Chomp, an Australian community-wide intervention program. Am J Clin Nutr. 2010. 91:831-40. doi:10.3945/ajcn.2009.28826. | Intervention/exposure; Outcome
236 | Deas, GW. Contribution of diet to the increased incidence of type 2 diabetes mellitus in inner city African-American children. Journal of Pediatric Endocrinology and Metabolism. 2002. 15:503-504. | Study design; Outcome
237 | DeClercq, V, Cui, Y, Forbes, C, Grandy, SA, Keats, M, Parker, L, Sweeney, E, Yu, ZM, Dummer, TJB. Association between Diet Quality and Adiposity in the Atlantic PATH Cohort. Nutrients. 2017. 9. doi:10.3390/nu9101155. | Study design
238 | Delahanty, L. Winning at losing: a guide to healthy weight loss. Meal replacements. Used correctly, weight-loss shakes and bars can offer nutritious options. Diabetes Forecast. 2002. 55:75-6, 78. | Study design; Publication status
239 | Dello Russo, M, Ahrens, W, De Henauw, S, Eiben, G, Hebestreit, A, Kourides, Y, Lissner, L, Molnar, D, Moreno, LA, Pala, V, Veidebaum, T, Siani, A, Russo, P. The Impact of Adding Sugars to Milk and Fruit on Adiposity and Diet Quality in Children: A Cross-Sectional and Longitudinal Analysis of the Identification and Prevention of Dietary- and Lifestyle-Induced Health Effects in Children and Infants (IDEFICS) Study. Nutrients. 2018. 10. doi:10.3390/nu10101350. | Intervention/exposure; Duplicate
240 | Demling, RH, DeSanti, L. Effect of a hypocaloric diet, increased protein intake and resistance training on lean mass gains and fat mass loss in overweight police officers. Ann Nutr Metab. 2000. 44:21-9. doi:10.1159/000012817. | Intervention/exposure; Comparator
241 | Dhingra, R, Sullivan, L, Jacques, PF, Wang, TJ, Fox, CS, Meigs, JB, D’Agostino, RB, Gaziano, JM, Vasan, RS. Soft drink consumption and risk of developing cardiometabolic risk factors and the metabolic syndrome in middle-aged adults in the community. Circulation. 2007. 116:480-8. doi:10.1161/circulationaha.107.689935. | Intervention/exposure
242 | Diaz-Lopez, A, Bullo, M, Martinez-Gonzalez, MA, Corella, D, Estruch, R, Fito, M, Gomez-Gracia, E, Fiol, M, Garcia de la Corte, FJ, Ros, E, Babio, N, Serra-Majem, L, Pinto, X, Munoz, MA, Frances, F, Buil-Cosiales, P, Salas-Salvado, J. Dairy product consumption and risk of type 2 diabetes in an elderly Spanish Mediterranean population at high cardiovascular risk. Eur J Nutr. 2016. 55:349-60. doi:10.1007/s00394-015-0855-8. | Outcome
243 | Diepvens, K, Kovacs, EM, Nijs, IM, Vogels, N, Westerterp-Plantenga, MS. Effect of green tea on resting energy expenditure and substrate oxidation during weight loss in overweight females. Br J Nutr. 2005. 94:1026-34. | Intervention/exposure
244 | Diepvens, K, Kovacs, EM, Vogels, N, Westerterp-Plantenga, MS. Metabolic effects of green tea and of phases of weight loss. Physiol Behav. 2006. 87:185-91. doi:10.1016/j.physbeh.2005.09.013. | Intervention/exposure
245 | Diepvens, K, Kovacs, EMR, Nijs, IMT, Vogels, N, Westerterp-Plantenga, MS. Effects of green tea on resting energy expenditure and substrate oxidation during weight loss in overweight females. British Journal of Nutrition. 2005. 94:1026-1034. doi:10.1079/BJN20051580. | Intervention/exposure
246 | DiMeglio, DP, Mattes, RD. Liquid versus solid carbohydrate: effects on food intake and body weight. Int J Obes Relat Metab Disord. 2000. 24:794-800. | Publication date
247 | Ditschuneit, HH, Flechtner-Mors, M. Value of structured meals for weight management: risk factors and long-term weight maintenance. Obes Res. 2001. 9 Suppl 4:284s-289s. doi:10.1038/oby.2001.132. | Intervention/exposure
248 | Dourado, GK, Cesar, TB. Investigation of cytokines, oxidative stress, metabolic, and inflammatory biomarkers after orange juice consumption by normal and overweight subjects. Food Nutr Res. 2015. 59:28147. doi:10.3402/fnr.v59.28147. | Study design
249 | Downs, SM, Marshall, D, Ng, C, Willows, ND. Central adiposity and associated lifestyle factors in Cree children. Appl Physiol Nutr Metab. 2008. 33:476-82. doi:10.1139/h08-027. | Study design
250 | Drake, I, Sonestedt, E, Ericson, U, Wallstrom, P, Orho-Melander, M. A Western dietary pattern is prospectively associated with cardio-metabolic traits and incidence of the metabolic syndrome. Br J Nutr. 2018. 119:1168-1176. doi:10.1017/s000711451800079x. | Intervention/exposure
251 | Driessen, MT, Koppes, LL, Veldhuis, L, Samoocha, D, Twisk, JW. Coffee consumption is not related to the metabolic syndrome at the age of 36 years: the Amsterdam Growth and Health Longitudinal Study. Eur J Clin Nutr. 2009. 63:536-42. doi:10.1038/ejcn.2008.6. | Intervention/exposure
252 | Drouin-Chartier, JP, Gagnon, J, Labonte, ME, Desroches, S, Charest, A, Grenier, G, Dodin, S, Lemieux, S, Couture, P, Lamarche, B. Impact of milk consumption on cardiometabolic risk in postmenopausal women with abdominal obesity. Nutr J. 2015. 14:12. doi:10.1186/1475-2891-14-12. | Outcome
253 | Du, H, van der, Dl A, Ginder, V, Jebb, SA, Forouhi, NG, Wareham, NJ, Halkjaer, J, Tjonneland, A, Overvad, K, Jakobsen, MU, Buijsse, B, Steffen, A, Palli, D, Masala, G, Saris, WH, Sorensen, TI, Feskens, EJ. Dietary energy density in relation to subsequent changes of weight and waist circumference in European men and women. PLoS One. 2009. 4:e5339. doi:10.1371/journal.pone.0005339. | Intervention/exposure
254 | Du, X, Zhu, K, Trube, A, Zhang, Q, Ma, G, Hu, X, Fraser, DR, Greenfield, H. School-milk intervention trial enhances growth and bone mineral accretion in Chinese girls aged 10-12 years in Beijing. Br J Nutr. 2004. 92:159-68. doi:10.1079/bjn20041118. | Comparator; Country
255 | Dubois, L, Farmer, A, Girard, M, Peterson, K. Regular sugar-sweetened beverage consumption between meals increases risk of overweight among preschool-aged children. J Am Diet Assoc. 2007. 107:924-34; discussion 934-5. doi:10.1016/j.jada.2007.03.004. | Publication date
256 | Dubois, L, Farmer, A, Girard, M, Peterson, K. Regular Sugar-Sweetened Beverage Consumption between Meals Increases Risk of Overweight among Preschool-Aged Children. Journal of the American Dietetic Association. 2007. 107:924-934. doi:10.1016/j.jada.2007.03.004. | Duplicate
257 | Dubois, L, Farmer, A, Girard, M, Peterson, K. Social factors and television use during meals and snacks is associated with higher BMI among pre-school children. Public Health Nutr. 2008. 11:1267-79. doi:10.1017/s1368980008002887. | Study design; Outcome
258 | Dubuisson, AC, Zech, FR, Dassy, MM, Jodogne, NB, Beauloye, VM. Determinants of weight loss in an interdisciplinary long-term care program for childhood obesity. ISRN Obes. 2012. 2012:349384. doi:10.5402/2012/349384. | Health status
259 | Dugan, CE, Aguilar, D, Park, YK, Lee, JY, Fernandez, ML. Dairy Consumption Lowers Systemic Inflammation and Liver Enzymes in Typically Low-Dairy Consumers with Clinical Characteristics of Metabolic Syndrome. Journal of the American College of Nutrition. 2016. 35:255-261. doi:10.1080/07315724.2015.1022637. | Intervention/exposure
260 | Durão, C, Severo, M, Oliveira, A, Moreira, P, Guerra, A, Barros, H, Lopes, C. Evaluating the effect of energy-dense foods consumption on preschool children’s body mass index: a prospective analysis from 2 to 4 years of age. European Journal of Nutrition. 2014. . doi:10.1007/s00394-014-0762-4. | Duplicate
261 | Eagle, TF, Gurm, R, Goldberg, CS, DuRussel-Weston, J, Kline-Rogers, E, Palma-Davis, L, Aaronson, S, Fitzgerald, CM, Mitchell, LR, Rogers, B, Bruenger, P, Jackson, EA, Eagle, KA. Health status and behavior among middle-school children in a midwest community: what are the underpinnings of childhood obesity?. Am Heart J. 2010. 160:1185-9. doi:10.1016/j.ahj.2010.09.019. | Study design
262 | Ebbeling, CB, Feldman, HA, Osganian, SK, Chomitz, VR, Ellenbogen, SJ, Ludwig, DS. Effects of decreasing sugar-sweetened beverage consumption on body weight in adolescents: a randomized, controlled pilot study. Pediatrics. 2006. 117:673-80. doi:10.1542/peds.2005-0983. | Publication date
263 | Economos, CD, Moore, CE, Hyatt, RR, Kuder, J, Chen, T, Meydani, SN, Meydani, M, Klein, E, Biancuzzo, RM, Holick, MF. Multinutrient-fortified juices improve vitamin D and vitamin E status in children: a randomized controlled trial. J Acad Nutr Diet. 2014. 114:709-17. doi:10.1016/j.jand.2013.07.027. | Outcome
264 | Efficacy of tea catechin-rich beverages to reduce abdominal adiposity and metabolic syndrome risks in obese and overweight subjects: a pooled analysis of 6 human trials. Nutrition research (new york, N.Y.). 2018. 55. | Study design
265 | Egawa, K, Yoshimura, M, Kanzaki, N, Nakamura, J, Kitagawa, Y, Shibata, H, Fukuhara, I. Body fat reducing effect and safety evaluation of long-term consumption of green tea containing quercetin glucoside in obese subjects. Japanese pharmacology and therapeutics. 2012. 40:495-503. | Language
266 | Ekhlasi, G, Shidfar, F, Agah, S, Merat, S, Hosseini, AF. Effects of Pomegranate and Orange Juice on Antioxidant Status in Non-Alcoholic Fatty Liver Disease Patients: A Randomized Clinical Trial. Int J Vitam Nutr Res. 2015. 85:292-298. doi:10.1024/0300-9831/a000292. | Health status
267 | Elinder, LS, Heinemans, N, Zeebari, Z, Patterson, E. Longitudinal changes in health behaviours and body weight among Swedish school children--associations with age, gender and parental education--the SCIP school cohort. BMC Public Health. 2014. 14:640. doi:10.1186/1471-2458-14-640. | Intervention/exposure
268 | Eliot, KA, Knehans, AW, Bemben, DA, Witten, MS, Carter, J, Bemben, MG. The effects of creatine and whey protein supplementation on body composition in men aged 48 to 72 years during resistance training. J Nutr Health Aging. 2008. 12:208-12. | Intervention/exposure; Comparator
269 | Elwood, PC, Pickering, JE, Fehily, AM. Milk and dairy consumption, diabetes and the metabolic syndrome: the Caerphilly prospective study. J Epidemiol Community Health. 2007. 61:695-8. doi:10.1136/jech.2006.053157. | Outcome
270 | Emond, JA, Patterson, RE, Jardack, PM, Arab, L. Using doubly labeled water to validate associations between sugar-sweetened beverage intake and body mass among White and African-American adults. Int J Obes (Lond). 2014. 38:603-9. doi:10.1038/ijo.2013.130. | Study design
271 | Enga, KF, Braekkan, SK, Hansen-Krone, IJ, Wilsgaard, T, Hansen, JB. Coffee consumption and the risk of venous thromboembolism: the Tromso study. J Thromb Haemost. 2011. 9:1334-9. doi:10.1111/j.1538-7836.2011.04353.x. | Outcome
272 | Engberink, MF, Geleijnse, JM, de Jong, N, Smit, HA, Kok, FJ, Verschuren, WM. Dairy intake, blood pressure, and incident hypertension in a general Dutch population. J Nutr. 2009. 139:582-7. doi:10.3945/jn.108.093088. | Outcome
273 | Engel, S, Tholstrup, T, Bruun, JM, Astrup, A, Richelsen, B, Raben, A. Effect of high milk and sugar-sweetened and non-caloric soft drink intake on insulin sensitivity after 6 months in overweight and obese adults: a randomized controlled trial. Eur J Clin Nutr. 2018. 72:358-366. doi:10.1038/s41430-017-0006-9. | Other (e.g., duplicative data)
274 | Engels, HJ, Gretebeck, RJ, Gretebeck, KA, Jimenez, L. Promoting healthful diets and exercise: efficacy of a 12-week after-school program in urban African Americans. J Am Diet Assoc. 2005. 105:455-9. doi:10.1016/j.jada.2004.12.003. | Intervention/exposure
275 | Erratum to Randomized, double-blind, placebo-controlled, linear dose, crossover study to evaluate the efficacy and safety of a green coffee bean extract in overweight subjects (Diabetes, Metabolic Syndrome and Obesity: targets and Therapy (2012), 5, (21-27)). Diabetes, metabolic syndrome and obesity: targets and therapy. 2014. 7:467. doi:10.2147/DMSO.S75357. | Publication status
276 | Esfarjani, F, Khalafi, M, Mohammadi, F, Mansour, A, Roustaee, R, Zamani-Nour, N, Kelishadi, R. Family-based intervention for childhood obesity: an experience among tehranian children. Annals of nutrition & metabolism. 2013. 63:844. doi:10.1159/000354245. | Intervention/exposure; Health status
277 | Eshak, ES, Iso, H, Kokubo, Y, Saito, I, Yamagishi, K, Inoue, M, Tsugane, S. Soft drink intake in relation to incident ischemic heart disease, stroke, and stroke subtypes in Japanese men and women: the Japan Public Health Centre-based study cohort I. Am J Clin Nutr. 2012. 96:1390-7. doi:10.3945/ajcn.112.037903. | Outcome
278 | Eshak, ES, Iso, H, Mizoue, T, Inoue, M, Noda, M, Tsugane, S. Soft drink, 100% fruit juice, and vegetable juice intakes and risk of diabetes mellitus. Clin Nutr. 2013. 32:300-8. doi:10.1016/j.clnu.2012.08.003. | Outcome
279 | Esmaeilinezhad, Z, Babajafari, S, Sohrabi, Z, Eskandari, MH, Amooee, S, Barati-Boldaji, R. Effect of synbiotic pomegranate juice on glycemic, sex hormone profile and anthropometric indices in PCOS: A randomized, triple blind, controlled trial. Nutr Metab Cardiovasc Dis. 2019. 29:201-208. doi:10.1016/j.numecd.2018.07.002. | Health status
280 | Esmarck, B, Andersen, JL, Olsen, S, Richter, EA, Mizuno, M, Kjaer, M. Timing of postexercise protein intake is important for muscle hypertrophy with resistance training in elderly humans. J Physiol. 2001. 535:301-11. doi:10.1111/j.1469-7793.2001.00301.x. | Intervention/exposure; Comparator
281 | Evans, EW, Must, A, Anderson, SE, Curtin, C, Scampini, R, Maslin, M, Bandini, L. Dietary Patterns and Body Mass Index in Children with Autism and Typically Developing Children. Res Autism Spectr Disord. 2012. 6:399-405. doi:10.1016/j.rasd.2011.06.014. | Study design
282 | Evans, M, Antony, J, Guthrie, N, Landes, B, Aruoma, OI. A Randomized Double-Blind, Placebo Controlled, Four-Arm Parallel Study Investigating the Effect of a Broad-Spectrum Wellness Beverage on Mood State in Healthy, Moderately Stressed Adults. Journal of the American College of Nutrition. 2018. 37:234-242. doi:10.1080/07315724.2017.1393356. | Intervention/exposure; Outcome
283 | Fagherazzi, G, Vilier, A, Saes Sartorelli, D, Lajous, M, Balkau, B, Clavel-Chapelon, F. Consumption of artificially and sugar-sweetened beverages and incident type 2 diabetes in the Etude Epidemiologique aupres des femmes de la Mutuelle Generale de l’Education Nationale-European Prospective Investigation into Cancer and Nutrition cohort. Am J Clin Nutr. 2013. 97:517-23. doi:10.3945/ajcn.112.050997. | Outcome
284 | Fagherazzi, G, Vilier, A, Sartorelli, DS, Lajous, M, Balkau, B, Clavel-Chapelon, F. Consumption of artificially and sugar-sweetened beverages and incident type 2 diabetes in the Etude Epidé miologique auprè s des femmes de la Mutuelle Gé né rale de l’Education Nationale-European Prospective Investigation into Cancer and Nutrition cohort1-4. American Journal of Clinical Nutrition. 2013. 97:517-523. doi:10.3945/ajcn.112.050997. | Outcome; Duplicate
285 | Faghih, S, Abadi, AR, Hedayati, M, Kimiagar, M. The effect of the combination of restricted energy diet and low fat milk or calcium supplement on iron status of premenopausal overweight or obese women. Clinical nutrition, supplement. 2012. 7:238-239. doi:10.1016/S1744-1161%2812%2970592-6. | Publication status
286 | Faghih, S, Hedayati, M, Abadi, A, Kimiagar, M. Comparing the effects of cow’s milk, and calcium supplementation on components of the metabolic syndrome in overweight or obese women. Iranian journal of endocrinology and metabolism. 2013. 14. | Other (e.g., duplicative data)
287 | Faghih, S, Hedayati, M, Abadi, A, Kimiagar, M. Comparison of the effects of cow’s milk, fortified soy milk, and calcium supplement on plasma adipocytokines in overweight and obese women. Iranian journal of endocrinology and metabolism. 2010. 11:692-698+739. | Language
288 | Faghih, S, Hedayati, M, Abadi, A, Kimiagar, SM. Comparison of the effects of cow’s milk, fortified soy milk, and calcium supplement on plasma adipocytokines in overweight or obese women. International Journal of Endocrinology and Metabolism. 2011. 8:188-193. | Other (e.g., duplicative data)
289 | Faith, MS, Rhea, SA, Corley, RP, Hewitt, JK. Genetic and shared environmental influences on children’s 24-h food and beverage intake: sex differences at age 7 y. Am J Clin Nutr. 2008. 87:903-11. doi:10.1093/ajcn/87.4.903. | Study design; Intervention/exposure
290 | Fakhouri, TH, Jahren, AH, Appel, LJ, Chen, L, Alavi, R, Anderson, CA. Serum carbon isotope values change in adults in response to changes in sugar-sweetened beverage intake. J Nutr. 2014. 144:902-5. doi:10.3945/jn.113.186213. | Intervention/exposure; Outcome
291 | Fallah, Z, Feizi, A, Hashemipour, M, Kelishadi, R. Effect of fermented camel milk on glucose metabolism, insulin resistance, and inflammatory biomarkers of adolescents with metabolic syndrome: A double-blind, randomized, crossover trial. J Res Med Sci. 2018. 23:32. doi:10.4103/jrms.JRMS_1191_17. | Outcome
292 | Fallah, Z, Feizi, A, Hashemipour, M, Kelishadi, R. Positive Effect of Fermented Camel Milk on Liver Enzymes of Adolescents with Metabolic Syndrome: a Double Blind, Randomized, Cross-over Trial. Mater Sociomed. 2018. 30:20-25. doi:10.5455/msm.2018.30.20-25. | Outcome
293 | Fantino, M, Fantino, A, Matray, M, Mistretta, F. Reprint of “Beverages containing low energy sweeteners do not differ from water in their effects on appetite, energy intake and food choices in healthy, non-obese French adults”. Appetite. 2018. 129:103-112. doi:10.1016/j.appet.2018.06.036. | Duration experimental study
294 | Fantino, M, Fantino, A, Mistretta, F, Bottigioli, D. Acute or long term consumption of beverages containing low calorie sweeteners do not alter appetite, energy intake or macronutrient selection in healthy adults: a non-inferiority comparison with water. Annals of nutrition & metabolism. 2017. 71:871-. doi:10.1159/000480486. | Publication status
295 | Fanti-Oren, S, Birenbaum-Carmeli, D, Eliakim, A, Pantanowitz, M, Nemet, D. The effect of placebo on endurance capacity in normal weight children - a randomized trial. BMC Pediatr. 2019. 19:15. doi:10.1186/s12887-019-1394-x. | Outcome
296 | Farzanegi, P, Samiee, M, Sabbaghian, Z. Interactive effect of regular aerobic training and milk consumption consumption on some inflammatory markers and lipid profile in overweight boys. Koomesh. 2016. 17:627-635. | Language
297 | Fathi, Y, Ghodrati, N, Zibaeenezhad, MJ, Faghih, S. Kefir drink causes a significant yet similar improvement in serum lipid profile, compared with low-fat milk, in a dairy-rich diet in overweight or obese premenopausal women: a randomized controlled trial. Journal of clinical lipidology. (no pagination), 2016. 2016. Date of Publication: January 10. doi:10.1016/j.jacl.2016.10.016. | Outcome
298 | Feeley, AB, Musenge, E, Pettifor, JM, Norris, SA. Investigation into longitudinal dietary behaviours and household socio-economic indicators and their association with BMI Z-score and fat mass in South African adolescents: the Birth to Twenty (Bt20) cohort. Public Health Nutr. 2013. 16:693-703. doi:10.1017/s1368980012003308. | Country
299 | Fekete, AA, Giromini, C, Chatzidiakou, Y, Givens, DI, Lovegrove, JA. Whey protein lowers blood pressure and improves endothelial function and lipid biomarkers in adults with prehypertension and mild hypertension: results from the chronic Whey2Go randomized controlled trial. Am J Clin Nutr. 2016. 104:1534-1544. doi:10.3945/ajcn.116.137919. | Comparator
300 | Ferreira, I, Twisk, JW, van Mechelen, W, Kemper, HC, Stehouwer, CD. Development of fatness, fitness, and lifestyle from adolescence to the age of 36 years: determinants of the metabolic syndrome in young adults: the amsterdam growth and health longitudinal study. Arch Intern Med. 2005. 165:42-8. doi:10.1001/archinte.165.1.42. | Intervention/exposure
301 | Feskanich, D, Bischoff-Ferrari, HA, Frazier, AL, Willett, WC. Milk consumption during teenage years and risk of hip fractures in older adults. JAMA Pediatrics. 2014. 168:54-60. doi:10.1001/jamapediatrics.2013.3821. | Outcome
302 | Fiatarone Singh, MA, Bernstein, MA, Ryan, AD, O’Neill, EF, Clements, KM, Evans, WJ. The effect of oral nutritional supplements on habitual dietary quality and quantity in frail elders. J Nutr Health Aging. 2000. 4:5-12. | Intervention/exposure; Comparator
303 | Fielding, R, Kirn, D, Koochek, A, Reid, K, Laussen, J, Gustafsson, T, Cederholm, T. Impactofa structured physical activity program and nutritional supplementation on regional body composition: results from the vitality, independence, and vigor in the elderly 2 study (VIVE2). Clinical nutrition. Conference: 38th european society for clinical nutrition and metabolism congress, ESPEN. Denmark. Conference start: 20160917. Conference end: 20160920. 2016. 35:S25. | Publication status
304 | Fisberg, M, de Oliveira, CL, de Padua Cintra, I, Losso, G, Bueno, MB, Rhein, SO, Maximino, P. Impact of the hypocaloric diet using food substitutes on the body weight and biochemical profile. Arch Latinoam Nutr. 2004. 54:402-7. | Intervention/exposure
305 | Flaim, C, Kob, M, Di Pierro, AM, Herrmann, M, Lucchin, L. Effects of a whey protein supplementation on oxidative stress, body composition and glucose metabolism among overweight people affected by diabetes mellitus or impaired fasting glucose: A pilot study. J Nutr Biochem. 2017. 50:95-102. doi:10.1016/j.jnutbio.2017.05.003. | Study design; Health status
306 | Flechtner-Mors, M, Boehm, BO, Wittmann, R, Thoma, U, Ditschuneit, HH. Enhanced weight loss with protein-enriched meal replacements in subjects with the metabolic syndrome. Diabetes Metab Res Rev. 2010. 26:393-405. doi:10.1002/dmrr.1097. | Intervention/exposure
307 | Fletcher, EA, Lamb, KE, McNaughton, SA, Garnett, SP, Dunstan, DW, Baur, LA, Salmon, J. Cross-sectional and prospective mediating effects of dietary intake on the relationship between sedentary behaviour and body mass index in adolescents. BMC Public Health. 2017. 17:751. doi:10.1186/s12889-017-4771-0. | Intervention/exposure
308 | Fletcher, J, Frisvold, D, Tefft, N. Substitution patterns can limit the effects of sugar-sweetened beverage taxes on obesity. Prev Chronic Dis. 2013. 10:E18. doi:10.5888/pcd10.120195. | Study design
309 | Flodin, L, Cederholm, T, Saaf, M, Samnegard, E, Ekstrom, W, Al-Ani, AN, Hedstrom, M. Effects of protein-rich nutritional supplementation and bisphosphonates on body composition, handgrip strength and health-related quality of life after hip fracture: a 12-month randomized controlled study. BMC Geriatr. 2015. 15:149. doi:10.1186/s12877-015-0144-7. | Intervention/exposure
310 | Flores, G, Lin, H. Factors predicting severe childhood obesity in kindergarteners. Int J Obes (Lond). 2013. 37:31-9. doi:10.1038/ijo.2012.168. | Intervention/exposure
311 | Fonolla-Joya, J, Reyes-García, R, García-Martín, A, López-Huertas, E, Muñoz-Torres, M. Daily Intake of Milk Enriched with n-3 Fatty Acids, Oleic Acid, and Calcium Improves Metabolic and Bone Biomarkers in Postmenopausal Women. Journal of the American College of Nutrition. 2016. 35:529-536. doi:10.1080/07315724.2014.1003114. | Comparator
312 | Fontaine, KR, Yang, D, Gadbury, GL, Heshka, S, Schwartz, LG, Murugesan, R, Kraker, JL, Heo, M, Heymsfield, SB, Allison, DB. Results of soy-based meal replacement formula on weight, anthropometry, serum lipids & blood pressure during a 40-week clinical weight loss trial. Nutr J. 2003. 2:14. doi:10.1186/1475-2891-2-14. | Intervention/exposure
313 | Food consumed in beverage form independently increases daily energy intake. Nature Clinical Practice Endocrinology and Metabolism. 2008. 4:122. doi:10.1038/ncpendmet0744. | Study design; Publication status
314 | Foroudi, S, Potter, AS, Stamatikos, A, Patil, BS, Deyhim, F. Drinking orange juice increases total antioxidant status and decreases lipid peroxidation in adults. J Med Food. 2014. 17:612-7. doi:10.1089/jmf.2013.0034. | Study design
315 | Fowler, SP, Williams, K, Resendez, RG, Hunt, KJ, Hazuda, HP, Stern, MP. Fueling the obesity epidemic? Artificially sweetened beverage use and long-term weight gain. Obesity (Silver Spring). 2008. 16:1894-900. doi:10.1038/oby.2008.284. | Publication date; Language
316 | Fowles, ER, Walker, LO. Correlates of dietary quality and weight retention in postpartum women. J Community Health Nurs. 2006. 23:183-97. doi:10.1207/s15327655jchn2303_5. | Study design
317 | Francis, P, Mc Cormack, W, Toomey, C, Norton, C, Saunders, J, Kerin, E, Lyons, M, Jakeman, P. Twelve weeks’ progressive resistance training combined with protein supplementation beyond habitual intakes increases upper leg lean tissue mass, muscle strength and extended gait speed in healthy older women. Biogerontology. 2017. 18:881-891. doi:10.1007/s10522-016-9671-7. | Intervention/exposure; Comparator
318 | Franckle, RL, Falbe, J, Gortmaker, S, Barrett, JL, Giles, C, Ganter, C, Blaine, RE, Buszkiewicz, J, Taveras, EM, Kwass, JA, Land, T, Davison, KK. Student obesity prevalence and behavioral outcomes for the massachusetts childhood obesity research demonstration project. Obesity (Silver Spring). 2017. 25:1175-1182. doi:10.1002/oby.21867. | Intervention/exposure
319 | Freak-Poli, RL, Wolfe, R, Walls, H, Backholer, K, Peeters, A. Participant characteristics associated with greater reductions in waist circumference during a four-month, pedometer-based, workplace health program. BMC Public Health. 2011. 11:824. doi:10.1186/1471-2458-11-824. | Intervention/exposure
320 | French, SA, Harnack, L, Jeffery, RW. Fast food restaurant use among women in the Pound of Prevention study: dietary, behavioral and demographic correlates. Int J Obes Relat Metab Disord. 2000. 24:1353-9. | Intervention/exposure
321 | French, SA, Sherwood, NE, JaKa, MM, Haapala, JL, Ebbeling, CB, Ludwig, DS. Physical changes in the home environment to reduce television viewing and sugar-sweetened beverage consumption among 5- to 12-year-old children: a randomized pilot study. Pediatr Obes. 2016. 11:e12-5. doi:10.1111/ijpo.12067. | Intervention/exposure; Comparator
322 | Fresan, U, Gea, A, Bes-Rastrollo, M, Basterra-Gortari, FJ, Carlos, S, Martinez-Gonzalez, MA. Substitution of water or fresh juice for bottled juice and type 2 diabetes incidence: The SUN cohort study. Nutrition, Metabolism and Cardiovascular Diseases. 2017. 27:874-880. doi:10.1016/j.numecd.2017.07.010. | Outcome
323 | Frestedt, J, Kolberg, L, Bell, M, Anderson, J. s-glucan beverage in individuals at high risk for diabetes mellitus. Annals of nutrition & metabolism. 2011. 58:24. doi:10.1159/000334393. | Publication status
324 | Frestedt, JL, Young, LR, Bell, M. Meal Replacement Beverage Twice a Day in Overweight and Obese Adults (MDRC2012-001). Curr Nutr Food Sci. 2012. 8:320-329. doi:10.2174/157340112803832156. | Study design
325 | Frestedt, JL, Zenk, JL, Kuskowski, MA, Ward, LS, Bastian, ED. A whey-protein supplement increases fat loss and spares lean muscle in obese subjects: a randomized human clinical study. Nutr Metab (Lond). 2008. 5:8. doi:10.1186/1743-7075-5-8. | Intervention/exposure; Health status
326 | Friberg, E, Orsini, N, Mantzoros, CS, Wolk, A. Coffee drinking and risk of endometrial cancer - A population-based cohort study. International Journal of Cancer. 2009. 125:2413-2417. doi:10.1002/ijc.24543. | Outcome
327 | Friedrich, M, Goluch-Koniuszy, Z. Assessment of influence of pro-health nutrition education and resulting changes of nutrition behavior of women aged 65-85 on their body content. Prz Menopauzalny. 2015. 14:223-30. doi:10.5114/pm.2015.55888. | Intervention/exposure
328 | Fujioka, K, Greenway, F, Sheard, J, Ying, Y. The effects of grapefruit on weight and insulin resistance: relationship to the metabolic syndrome. J Med Food. 2006. 9:49-54. doi:10.1089/jmf.2006.9.49. | Health status
329 | Fukino, Y, Ikeda, A, Maruyama, K, Aoki, N, Okubo, T, Iso, H. Randomized controlled trial for an effect of green tea-extract powder supplementation on glucose abnormalities. Eur J Clin Nutr. 2008. 62:953-60. doi:10.1038/sj.ejcn.1602806. | Intervention/exposure
330 | Fukino, Y, Shimbo, M, Aoki, N, Okubo, T, Iso, H. Randomized controlled trial for an effect of green tea consumption on insulin resistance and inflammation markers. J Nutr Sci Vitaminol (Tokyo). 2005. 51:335-42. | Intervention/exposure
331 | Fumeron, F, Lamri, A, Abi Khalil, C, Jaziri, R, Porchay-Balderelli, I, Lantieri, O, Vol, S, Balkau, B, Marre, M. Dairy consumption and the incidence of hyperglycemia and the metabolic syndrome: results from a french prospective study, Data from the Epidemiological Study on the Insulin Resistance Syndrome (DESIR). Diabetes Care. 2011. 34:813-7. doi:10.2337/dc10-1772. | Intervention/exposure; Outcome
332 | Fung, TT, Arasaratnam, MH, Grodstein, F, Katz, JN, Rosner, B, Willett, WC, Feskanich, D. Soda consumption and risk of hip fractures in postmenopausal women in the Nurses’ Health Study. Am J Clin Nutr. 2014. 100:953-8. doi:10.3945/ajcn.114.083352. | Outcome
333 | Fung, TT, Malik, V, Rexrode, KM, Manson, JE, Willett, WC, Hu, FB. Sweetened beverage consumption and risk of coronary heart disease in women. Am J Clin Nutr. 2009. 89:1037-42. doi:10.3945/ajcn.2008.27140. | Outcome
334 | Galimov, A, Hanewinkel, R, Hansen, J, Unger, JB, Sussman, S, Morgenstern, M. Energy drink consumption among German adolescents: Prevalence, correlates, and predictors of initiation. Appetite. 2019. 139:172-179. doi:10.1016/j.appet.2019.04.016. | Outcome
335 | Galloway, T, Young, TK, Egeland, GM. Emerging obesity among preschool-aged Canadian Inuit children: results from the Nunavut Inuit Child Health Survey. Int J Circumpolar Health. 2010. 69:151-7. doi:10.3402/ijch.v69i2.17437. | Study design
336 | Garcia, DO, Morrill, KE, Aceves, B, Valdez, LA, Rabe, BA, Bell, ML, Hakim, IA, Martinez, JA, Thomson, CA. Feasibility and acceptability of a beverage intervention for Hispanic adults: results from a pilot randomized controlled trial. Public Health Nutr. 2019. 22:542-552. doi:10.1017/s1368980018003051. | Health status
337 | Gardener, H, Moon, YP, Rundek, T, Elkind, MSV, Sacco, RL. Diet Soda and Sugar-Sweetened Soda Consumption in Relation to Incident Diabetes in the Northern Manhattan Study. Curr Dev Nutr. 2018. 2:nzy008. doi:10.1093/cdn/nzy008. | Outcome
338 | Garduno-Diaz, SD, Khokhar, S. South Asian dietary patterns and their association with risk factors for the metabolic syndrome. J Hum Nutr Diet. 2013. 26:145-55. doi:10.1111/j.1365-277X.2012.01284.x. | Study design; Intervention/exposure
339 | Gaskin, PS, Lai, P, Guy, D, Knight, J, Jackson, M, Nielsen, AL. Diet, physical activity, weight status, and culture in a sample of children from the developing world. J Nutr Metab. 2012. 2012:242875. doi:10.1155/2012/242875. | Study design
340 | Gates, M, Hanning, RM, Gates, A, Martin, ID, Tsuji, LJ. Intakes of milk and alternatives among on-reserve First Nations youth in northern and southern Ontario, Canada. Public Health Nutr. 2013. 16:515-23. doi:10.1017/s1368980012003035. | Study design
341 | Geidl, B, Hochuli, M, Spinas, GA, Gerber, PA. Consumption of Sugar-Sweetened Beverages impairs the LDL Subclass profile-Data from a double-blind randomized controlled trial. Obesity facts. 2018. 11:191-192. doi:10.1159/000489691. | Publication status
342 | Geller, JS, Dube, ET, Cruz, GA, Stevens, J, Keating Bench, K. Pediatric Obesity Empowerment Model Group Medical Visits (POEM-GMV) as Treatment for Pediatric Obesity in an Underserved Community. Child Obes. 2015. 11:638-46. doi:10.1089/chi.2014.0163. | Intervention/exposure
343 | Ghavipour, M, Saedisomeolia, A, Djalali, M, Sotoudeh, G, Eshraghyan, MR, Moghadam, AM, Wood, LG. Tomato juice consumption reduces systemic inflammation in overweight and obese females. Br J Nutr. 2013. 109:2031-5. doi:10.1017/s0007114512004278. | Outcome
344 | Ghavipour, M, Sotoudeh, G, Ghorbani, M. Tomato juice consumption improves blood antioxidative biomarkers in overweight and obese females. Clin Nutr. 2015. 34:805-9. doi:10.1016/j.clnu.2014.10.012. | Outcome
345 | Gibbons, MJ, Gilchrist, NL, Frampton, C, Maguire, P, Reilly, PH, March, RL, Wall, CR. The effects of a high calcium dairy food on bone health in pre-pubertal children in New Zealand. Asia Pac J Clin Nutr. 2004. 13:341-7. | Comparator
346 | Gibbs, BB, Tudorascu, D, Bryce, C, Comer, D, Fischer, G, Hess, R, Huber, K, McTigue, K, Simkin-Silverman, L, Conroy, MB. Dietary habits associated with 6-and 24-month weight loss maintenance in primary care patients. Circulation. 2018. 137. | Publication status
347 | Giggey, PP, Wendell, CR, Zonderman, AB, Waldstein, SR. Greater coffee intake in men is associated with steeper age-related increases in blood pressure. Am J Hypertens. 2011. 24:310-5. doi:10.1038/ajh.2010.225. | Outcome
348 | Gilardini, L, Pasqualinotto, L, Di Pierro, F, Risso, P, Invitti, C. Effects of Greenselect Phytosome on weight maintenance after weight loss in obese women: a randomized placebo-controlled study. BMC complementary and alternative medicine. 2016. 16. doi:10.1186/s12906-016-1214-x. | Intervention/exposure; Health status
349 | Gilbert, JA, Joanisse, DR, Chaput, JP, Miegueu, P, Cianflone, K, Almeras, N, Tremblay, A. Milk supplementation facilitates appetite control in obese women during weight loss: a randomised, single-blind, placebo-controlled trial. Br J Nutr. 2011. 105:133-43. doi:10.1017/s0007114510003119. | Comparator
350 | Giri, A, Sturgeon, SR, Luisi, N, Bertone-Johnson, E, Balasubramanian, R, Reeves, KW. Caffeinated coffee, decaffeinated coffee and endometrial cancer risk: a prospective cohort study among US postmenopausal women. Nutrients. 2011. 3:937-50. doi:10.3390/nu3110937. | Outcome
351 | Godakanda, I, Abeysena, C, Lokubalasooriya, A. Sedentary behavior during leisure time, physical activity and dietary habits as risk factors of overweight among school children aged 14-15 years: case control study. BMC Res Notes. 2018. 11:186. doi:10.1186/s13104-018-3292-y. | Study design
352 | Gonzalez-Ortiz, M, Martinez-Abundis, E, Espinel-Bermudez, MC, Perez-Rubio, KG. Effect of pomegranate juice on insulin secretion and sensitivity in patients with obesity. Ann Nutr Metab. 2011. 58:220-3. doi:10.1159/000330116. | Health status
353 | Gonzalez-Suarez, CB, Lee-Pineda, K, Caralipio, ND, Grimmer-Somers, K, Sibug, EO, Velasco, ZF. Is what Filipino children eat between meals associated with body mass index?. Asia Pac J Public Health. 2015. 27:Np650-61. doi:10.1177/1010539513491416. | Study design
354 | Gopinath, B, Louie, JC, Flood, VM, Burlutsky, G, Hardy, LL, Baur, LA, Mitchell, P. Influence of obesogenic behaviors on health-related quality of life in adolescents. Asia Pac J Clin Nutr. 2014. 23:121-7. doi:10.6133/apjcn.2014.23.1.13. | Intervention/exposure; Outcome
355 | Gordillo, Bastidas, E, , Yanez, Sanchez, I, , Panduro, , A, . Effect of moderate-fat diet complemented with green tea on anthropometric and biochemical markers, and cardiovascular risk in obese patients. Diabetes & vascular disease research. 2011. 8. | Publication status
356 | Gorna, I, Kowalowka, M, Morawska, A, Kosewski, G, Boleslawska, I, Przyslawskia, J. Influence of the frequency of consumption of foodstuffs on the risk of overweight and obesity in a group of post-menopausal women. Prz Menopauzalny. 2019. 18:39-45. doi:10.5114/pm.2019.84156. | Study design
357 | Gouni-Berthold, I, Schulte, DM, Krone, W, Lapointe, JF, Lemieux, P, Predel, HG, Berthold, HK. The whey fermentation product malleable protein matrix decreases TAG concentrations in patients with the metabolic syndrome: A randomised placebo-controlled trial. British Journal of Nutrition. 2012. 107:1694-1706. doi:10.1017/S0007114511004843. | Intervention/exposure; Comparator
358 | Gradidge, PJL, Kruger, HS. Comparing beverage consumption, physical activity and anthropometry among young adult urban- and rural-dwelling African women. South African Journal of Clinical Nutrition. 2018. . doi:10.1080/16070658.2018.1540212. | Study design
359 | Grydeland, M, Bergh, IH, Bjelland, M, Lien, N, Andersen, LF, Ommundsen, Y, Klepp, KI, Anderssen, SA. Correlates of weight status among Norwegian 11-year-olds: The HEIA study. BMC Public Health. 2012. 12:1053. doi:10.1186/1471-2458-12-1053. | Study design
360 | Grynbaum, MM. Will soda restrictions help New York win the war on obesity?. Bmj. 2012. 345:e6768. doi:10.1136/bmj.e6768. | Study design
361 | Gryson, C, Ratel, S, Rance, M, Penando, S, Bonhomme, C, Le Ruyet, P, Duclos, M, Boirie, Y, Walrand, S. Four-month course of soluble milk proteins interacts with exercise to improve muscle strength and delay fatigue in elderly participants. J Am Med Dir Assoc. 2014. 15:958.e1-9. doi:10.1016/j.jamda.2014.09.011. | Comparator
362 | Guerin-Deremaux, L, Li, S, Pochat, M, Wils, D, Mubasher, M, Reifer, C, Miller, LE. Effects of NUTRIOSE(R) dietary fiber supplementation on body weight, body composition, energy intake, and hunger in overweight men. Int J Food Sci Nutr. 2011. 62:628-35. doi:10.3109/09637486.2011.569492. | Intervention/exposure
363 | Guérin-Deremaux, L, Li, S, Pochat, M, Wils, D, Mubasher, M, Reifer, C, Miller, LE. Effects of NUTRIOSE® dietary fiber supplementation on body weight, body composition, energy intake, and hunger in overweight men. International Journal of Food Sciences and Nutrition. 2011. 62:628-635. doi:10.3109/09637486.2011.569492. | Intervention/exposure; Comparator; Duplicate
364 | Guerin-Deremaux, L, Pochat, M, Reifer, C, Wils, D, Cho, S, Miller, LE. The soluble fiber NUTRIOSE induces a dose-dependent beneficial impact on satiety over time in humans. Nutr Res. 2011. 31:665-72. doi:10.1016/j.nutres.2011.09.004. | Intervention/exposure; Outcome
365 | Guess, N, Wijesuriya, M, Vasantharajah, L, Gulliford, M, Viberti, G, Gnudi, L, Karalliedde, J. The effect of dietary changes on distinct components of the metabolic syndrome in a young Sri Lankan population at high risk of CVD. Br J Nutr. 2016. 116:719-27. doi:10.1017/s0007114516002476. | Intervention/exposure
366 | Guevara, DA, Reyes, S, Lopez, M, Flores, N, Aguirre, S, Munoz, EB, Fornasini, M, Baldeon, ME. Impact of milk based micronutrient supplementation in school children in Quito-Ecuador. Nutr Hosp. 2017. 35:50-58. doi:10.20960/nh.1353. | Comparator
367 | Guilloty, NI, Soto, R, Anzalota, L, Rosario, Z, Cordero, JF, Palacios, C. Diet, Pre-pregnancy BMI, and Gestational Weight Gain in Puerto Rican Women. Matern Child Health J. 2015. 19:2453-61. doi:10.1007/s10995-015-1764-4. | Study design
368 | Gunther, AL, Stahl, LJ, Buyken, AE, Kroke, A. Association of dietary energy density in childhood with age and body fatness at the onset of the pubertal growth spurt. Br J Nutr. 2011. 106:345-9. doi:10.1017/s0007114511001772. | Intervention/exposure
369 | Gunther, CW, Lyle, RM, Legowski, PA, James, JM, McCabe, LD, McCabe, GP, Peacock, M, Teegarden, D. Fat oxidation and its relation to serum parathyroid hormone in young women enrolled in a 1-y dairy calcium intervention. Am J Clin Nutr. 2005. 82:1228-34. doi:10.1093/ajcn/82.6.1228. | Intervention/exposure
370 | Guo, X, Xu, Y, He, H, Cai, H, Zhang, J, Li, Y, Yan, X, Zhang, M, Zhang, N, Maddela, RL, Nicodemus-Johnson, J, Ma, G. Effects of a Meal Replacement on Body Composition and Metabolic Parameters among Subjects with Overweight or Obesity. J Obes. 2018. 2018:2837367. doi:10.1155/2018/2837367. | Intervention/exposure
371 | Habauzit, V, Verny, MA, Milenkovic, D, Barber-Chamoux, N, Mazur, A, Dubray, C, Morand, C. Flavanones protect from arterial stiffness in postmenopausal women consuming grapefruit juice for 6 mo: a randomized, controlled, crossover trial. Am J Clin Nutr. 2015. 102:66-74. doi:10.3945/ajcn.114.104646. | Comparator
372 | Haddock, CK, Poston, WS, Foreyt, JP, DiBartolomeo, JJ, Warner, PO. Effectiveness of Medifast supplements combined with obesity pharmacotherapy: a clinical program evaluation. Eat Weight Disord. 2008. 13:95-101. | Study design; Intervention/exposure
373 | Haddock, CK, Poston, WS, Lagrotte, C, Klotz, AA, Oliver, TL, Vander Veur, SS, Foster, GD, Jebb, SA, Moore, C, Roberts, SA, Reeves, RS, Bolton, MP, Foreyt, JP. Findings from an online behavioural weight management programme provided with or without a fortified diet beverage. Br J Nutr. 2014. 111:372-9. doi:10.1017/s0007114513002377. | Intervention/exposure
374 | Hagele, FA, Busing, F, Nas, A, Aschoff, J, Gnadinger, L, Schweiggert, R, Carle, R, Bosy-Westphal, A. High orange juice consumption with or in-between three meals a day differently affects energy balance in healthy subjects. Nutr Diabetes. 2018. 8:19. doi:10.1038/s41387-018-0031-3. | Comparator
375 | Hajna, S, Leblanc, PJ, Faught, BE, Merchant, AT, Cairney, J, Hay, J, Liu, J. Associations between family eating behaviours and body composition measures in peri-adolescents: results from a community-based study of school-aged children. Can J Public Health. 2014. 105:e15-21. | Study design
376 | Halkjaer, J, Sorensen, TI, Tjonneland, A, Togo, P, Holst, C, Heitmann, BL. Food and drinking patterns as predictors of 6-year BMI-adjusted changes in waist circumference. Br J Nutr. 2004. 92:735-48. | Intervention/exposure
377 | Hambre, D, Vergara, M, Lood, Y, Bachrach-Lindstrom, M, Lindstrom, T, Nystrom, FH. A randomized trial of protein supplementation compared with extra fast food on the effects of resistance training to increase metabolism. Scand J Clin Lab Invest. 2012. 72:471-8. doi:10.3109/00365513.2012.698021. | Intervention/exposure; Comparator
378 | Hameid, SA, Rahman, A, Abdulhadi, FS, Sattar, DA. Evaluation of the effect of the tea and body mass index on the blood indicators of pregnant women. Biochemical and Cellular Archives. 2018. 18:55-58. | Country
379 | Hamilton-Reeves, JM, Rebello, SA, Thomas, W, Slaton, JW, Kurzer, MS. Isoflavone-rich soy protein isolate suppresses androgen receptor expression without altering estrogen receptor-β expression or serum hormonal profiles in men at high risk of prostate cancer. Journal of Nutrition. 2007. 137:1769-1775. | Intervention/exposure; Comparator
380 | Hansen, CK, Klingenberg, L, Larsen, LB, Lorenzen, JK, Sorensen, KV, Astrup, A. The effect of UHT-processed dairy milk on cardio-metabolic risk factors. Eur J Clin Nutr. 2017. 71:1463-1466. doi:10.1038/ejcn.2017.22. | Comparator
381 | Harada, U, Chikama, A, Saito, S, Takase, H, Nagao, T, Hase, T, Tokimitsu, I. Effects of the long-term ingestion of tea catechins on energy expenditure and dietary fat oxidation in healthy subjects. Journal of Health Science. 2005. 51:248-252. doi:10.1248/jhs.51.248. | Comparator; Outcome
382 | Harris, C, Flexeder, C, Thiering, E, Buyken, A, Berdel, D, Koletzko, S, Bauer, CP, Bruske, I, Koletzko, B, Standl, M. Changes in dietary intake during puberty and their determinants: results from the GINIplus birth cohort study. BMC Public Health. 2015. 15:841. doi:10.1186/s12889-015-2189-0. | Intervention/exposure; Outcome
383 | Hartman, JW, Tang, JE, Wilkinson, SB, Tarnopolsky, MA, Lawrence, RL, Fullerton, AV, Phillips, SM. Consumption of fat-free fluid milk after resistance exercise promotes greater lean mass accretion than does consumption of soy or carbohydrate in young, novice, male weightlifters. Am J Clin Nutr. 2007. 86:373-81. doi:10.1093/ajcn/86.2.373. | Intervention/exposure; Comparator
384 | Hasanbegovic, S, Mesihovic-Dinarevic, S, Cuplov, M, Hadzimuratovic, A, Boskailo, H, Ilic, N, Njuhovic, A, Cengic, N, Bajramovic, E, Brkovic, S. Epidemiology and etiology of obesity in children and youth of Sarajevo Canton. Bosn J Basic Med Sci. 2010. 10:140-6. doi:10.17305/bjbms.2010.2713. | Study design
385 | Hassan, NE, Wahba, S, El-Alameey, IR, El-Masry, SA, AbuShady, MM, Hameed, ER, Ibrahim, TS, Boseila, S. Dietary Behaviour Pattern and Physical Activity in Overweight and Obese Egyptian Mothers: Relationships with Their Children’s Body Mass Index. Open Access Maced J Med Sci. 2016. 4:353-358. doi:10.3889/oamjms.2016.095. | Study design
386 | Hasselbalch, AL, Heitmann, BL, Kyvik, KO, Sorensen, TI. Associations between dietary intake and body fat independent of genetic and familial environmental background. Int J Obes (Lond). 2010. 34:892-8. doi:10.1038/ijo.2010.1. | Publication date
387 | Haub, MD, Simons, TR, Cook, CM, Remig, VM, Al-Tamimi, EK, Holcomb, CA. Calcium-fortified beverage supplementation on body composition in postmenopausal women. Nutr J. 2005. 4:21. doi:10.1186/1475-2891-4-21. | Intervention/exposure
388 | Hauge Wennersberg, M, Smedman, A, Turpeinen, A, Retterstl, K, Tengblad, S, Lipre, E, Aro, A, Mutanen, P, Seljeflot, I, Basu, S, etal, . Addition of milk products in the diet of overweight subjects has small effects on metabolic variables. Journal of diabetes. 2009. 1:A274. doi:10.1111/j.1753-0407.2009.00020.x. | Intervention/exposure; Publication status
389 | Hautaniemi, EJ, Tikkakoski, AJ, Tahvanainen, A, Nordhausen, K, Kähönen, M, Mattsson, T, Luhtala, S, Turpeinen, AM, Niemelä, O, Vapaatalo, H, Korpela, R, Pörsti, IH. Effect of fermented milk product containing lactotripeptides and plant sterol esters on haemodynamics in subjects with the metabolic syndrome - A randomised, double-blind, placebo-controlled study. British Journal of Nutrition. 2015. 114:376-386. doi:10.1017/S0007114515002032. | Intervention/exposure
390 | Hayashino, Y, Fukuhara, S, Okamura, T, Tanaka, T, Ueshima, H. High oolong tea consumption predicts future risk of diabetes among Japanese male workers: a prospective cohort study. Diabet Med. 2011. 28:805-10. doi:10.1111/j.1464-5491.2011.03239.x. | Outcome
391 | Hays, NP, Kim, H, Wells, AM, Kajkenova, O, Evans, WJ. Effects of whey and fortified collagen hydrolysate protein supplements on nitrogen balance and body composition in older women. J Am Diet Assoc. 2009. 109:1082-7. doi:10.1016/j.jada.2009.03.003. | Intervention/exposure; Comparator
392 | Hedrick, VE, Davy, BM, Myers, EA, You, W, Zoellner, JM. Changes in the Healthy Beverage Index in Response to an Intervention Targeting a Reduction in Sugar-Sweetened Beverage Consumption as Compared to an Intervention Targeting Improvements in Physical Activity: Results from the Talking Health Trial. Nutrients. 2015. 7:10168-78. doi:10.3390/nu7125525. | Comparator; Outcome
393 | Hedrick, VE, Davy, BM, You, W, Porter, KJ, Estabrooks, PA, Zoellner, JM. Dietary quality changes in response to a sugar-sweetened beverage-reduction intervention: Results from the Talking Health randomized controlled clinical trial. American Journal of Clinical Nutrition. 2017. 105:824-833. doi:10.3945/ajcn.116.144543. | Outcome
394 | Heiss, CJ, Naylor, J, Bronco, KM, Myers, BJ. A small food or fluid load has no effect on body composition measured by 3 different methods. Topics in Clinical Nutrition. 2008. 23:229-233. doi:10.1097/01.TIN.0000333555.38627.56. | Intervention/exposure; Comparator
395 | Heitor, SF, Rodrigues, LR, Tavares, DM. Factors associated with metabolic complications and feeding in elderly from the rural area. Cien Saude Colet. 2016. 21:3357-3366. doi:10.1590/1413-812320152111.11592015. | Study design
396 | Hemmingsson, E, Johansson, K, Eriksson, J, Sundstrom, J, Neovius, M, Marcus, C. Weight loss and dropout during a commercial weight-loss program including a very-low-calorie diet, a low-calorie diet, or restricted normal food: observational cohort study. Am J Clin Nutr. 2012. 96:953-61. doi:10.3945/ajcn.112.038265. | Intervention/exposure
397 | Herbenick, SK, James, K, Milton, J, Cannon, D. Effects of family nutrition and physical activity screening for obesity risk in school-age children. J Spec Pediatr Nurs. 2018. 23:e12229. doi:10.1111/jspn.12229. | Study design; Intervention/exposure
398 | Hermansen, K, Bohl, M, Gregersen, S. Dairy lipids, proteins, and abdominal obesity (Dairy Health): a 12-week, randomised, parallel-controlled, human intervention study. Diabetologia.. 2014. 57:S298. doi:10.1007/s00125-014-3355-0. | Publication status
399 | Hermansen, K, Gregersen, S, Larsen, MK, Bjoernshave, A, Larsen, MB. Beneficial effects of medium-chain saturated dairy fat on the body composition of abdominal obese subjects (dairyhealth): a 12-week, randomized, double-blinded, intervention study. Diabetes.. 2015. 64:A208-A209. doi:10.2337/db15742931. | Publication status
400 | Hernandez-Cordero, S, Barquera, S, Rodriguez-Ramirez, S, Villanueva-Borbolla, MA, Gonzalez de Cossio, T, Dommarco, JR, Popkin, B. Substituting water for sugar-sweetened beverages reduces circulating triglycerides and the prevalence of metabolic syndrome in obese but not in overweight Mexican women in a randomized controlled trial. J Nutr. 2014. 144:1742-52. doi:10.3945/jn.114.193490. | Intervention/exposure
401 | Hernandez-Cordero, S, Popkin, BM. Impact of a Water Intervention on Sugar-Sweetened Beverage Intake Substitution by Water: A Clinical Trial in Overweight and Obese Mexican Women. Ann Nutr Metab. 2015. 66 Suppl 3:22-5. doi:10.1159/000381242. | Intervention/exposure
402 | Higgins, KA, Considine, RV, Mattes, RD. Aspartame Consumption for 12 Weeks Does Not Affect Glycemia, Appetite, or Body Weight of Healthy, Lean Adults in a Randomized Controlled Trial. J Nutr. 2018. 148:650-657. doi:10.1093/jn/nxy021. | Intervention/exposure
403 | Hill, SE, Prokosch, ML, Morin, A, Rodeheffer, CD. The effect of non-caloric sweeteners on cognition, choice, and post-consumption satisfaction. Appetite. 2014. 83:82-8. doi:10.1016/j.appet.2014.08.003. | Outcome
404 | Hirose, A, Terauchi, M, Tamura, M, Akiyoshi, M, Owa, Y, Kato, K, Kubota, T. Tomato juice intake increases resting energy expenditure and improves hypertriglyceridemia in middle-aged women: an open-label, single-arm study. Nutr J. 2015. 14:34. doi:10.1186/s12937-015-0021-4. | Study design
405 | Hirota, T, Kawasaki, I, Hirota, K. Dairy calcium intake accompanied with higher intake of vitamin D could efficiently decrease body fat mass and increase lean mass without decreasing BMD during moderate weight loss in normal weight young Japanese women. Journal of bone and mineral research. 2011. 26. | Publication status
406 | Hirota, T, Kawasaki, I, Hirota, K. Milk intake accompanied with higher intake of vitamin D might efficiently decrease body fat mass and increase lean mass during moderate weight loss in normal weight young Japanese women. Osteoporosis international.. 2010. 21:S98. doi:10.1007/s00198-010-1247-9. | Publication status
407 | Hirota, T, Kusu, T, Hirota, K. Improvement of nutrition stimulates bone mineral gain in Japanese school children and adolescents. Osteoporosis International. 2005. 16:1057-1064. doi:10.1007/s00198-004-1804-1. | Outcome
408 | Hirschler, V, Buzzano, K, Erviti, A, Ismael, N, Silva, S, Dalamon, R. Overweight and lifestyle behaviors of low socioeconomic elementary school children in Buenos Aires. BMC Pediatr. 2009. 9:17. doi:10.1186/1471-2431-9-17. | Study design
409 | Ho, SC, Guldan, GS, Woo, J, Yu, R, Tse, MM, Sham, A, Cheng, J. A prospective study of the effects of 1-year calcium-fortified soy milk supplementation on dietary calcium intake and bone health in Chinese adolescent girls aged 14 to 16. Osteoporosis International. 2005. 16:1907-1916. doi:10.1007/s00198-005-1963-8. | Comparator
410 | Hoare, E, Millar, L, Fuller-Tyszkiewicz, M, Skouteris, H, Nichols, M, Malakellis, M, Swinburn, B, Allender, S. Depressive symptomatology, weight status and obesogenic risk among Australian adolescents: a prospective cohort study. BMJ Open. 2016. 6:e010072. doi:10.1136/bmjopen-2015-010072. | Outcome
411 | Hochstenbach-Waelen, A, Soenen, S, Westerterp, KR, Westerterp-Plantenga, MS. Effects of a supra-sustained gelatin-milk protein diet compared with (supra-)sustained milk protein diets on body-weight loss. Br J Nutr. 2011. 105:1388-98. doi:10.1017/s0007114510005106. | Intervention/exposure
412 | Hodge, AM, Bassett, JK, Milne, RL, English, DR, Giles, GG. Consumption of sugar-sweetened and artificially sweetened soft drinks and risk of obesity-related cancers. Public Health Nutr. 2018. 21:1618-1626. doi:10.1017/s1368980017002555. | Study design; Outcome
413 | Homayon, M. Preventing childhood obesity by reducing consumption of carbonated drinks: cluster randomised controlled trial. Hormone research in paediatrics. 2013. 80:242-. | Publication status
414 | Hooshmand, F, Asghari, G, Yuzbashian, E, Mahdavi, M, Mirmiran, P, Azizi, F. Modified Healthy Eating Index and Incidence of Metabolic Syndrome in Children and Adolescents: Tehran Lipid and Glucose Study. J Pediatr. 2018. 197:134-139.e2. doi:10.1016/j.jpeds.2018.01.080. | Intervention/exposure; Outcome
415 | Hosseini-Esfahani, F, Mirmiran, P, Daneshpour, MS, Mehrabi, Y, Hedayati, M, Zarkesh, M, Azizi, F. Western dietary pattern interaction with APOC3 polymorphism in the risk of metabolic syndrome: Tehran Lipid and Glucose Study. J Nutrigenet Nutrigenomics. 2014. 7:105-17. doi:10.1159/000365445. | Country
416 | Hostmark, AT, Sogaard, AJ, Alvaer, K, Meyer, HE. The oslo health study: a dietary index estimating frequent intake of soft drinks and rare intake of fruit and vegetables is negatively associated with bone mineral density. J Osteoporos. 2011. 2011:102686. doi:10.4061/2011/102686. | Study design; Outcome
417 | Hostmark, AT. The Oslo Health Study: a Dietary Index estimating high intake of soft drinks and low intake of fruits and vegetables was positively associated with components of the metabolic syndrome. Appl Physiol Nutr Metab. 2010. 35:816-25. doi:10.1139/h10-080. | Study design
418 | Hostmark, AT. The Oslo health study: soft drink intake is associated with the metabolic syndrome. Appl Physiol Nutr Metab. 2010. 35:635-42. doi:10.1139/h10-059. | Study design
419 | Hu, G, Jousilahti, P, Peltonen, M, Bidel, S, Tuomilehto, J. Joint association of coffee consumption and other factors to the risk of type 2 diabetes: a prospective study in Finland. Int J Obes (Lond). 2006. 30:1742-9. doi:10.1038/sj.ijo.0803341. | Outcome
420 | Hu, R, Fei, J, Zhai, Y, Feng, Y, Warren, J, Jin, Y, Papi, B, Stahl, B, Wang, Z, Li, J. The dietary intake of two groups of lactating women in Shanghai during the puerperium. Asia Pacific journal of clinical nutrition. 2019. 28:106-115. doi:10.6133/apjcn.201903_28(1).0015. | Intervention/exposure; Outcome
421 | Huang, M, Quddus, A, Stinson, L, Shikany, JM, Howard, BV, Kutob, RM, Lu, B, Manson, JE, Eaton, CB. Artificially sweetened beverages, sugar-sweetened beverages, plain water, and incident diabetes mellitus in postmenopausal women: the prospective Women’s Health Initiative observational study. Am J Clin Nutr. 2017. 106:614-622. doi:10.3945/ajcn.116.145391. | Outcome
422 | Huang, S, Li, J, Wu, Y, Ranjbar, S, Xing, A, Zhao, H, Wang, Y, Shearer, GC, Bao, L, Lichtenstein, AH, Wu, S, Gao, X. Tea consumption and longitudinal change in high-density lipoprotein cholesterol concentration in Chinese adults. Journal of the American Heart Association. 2018. 7. doi:10.1161/JAHA.118.008814. | Outcome
423 | Hudgins, LC, Hellerstein, MK, Seidman, CE, Neese, RA, Tremaroli, JD, Hirsch, J. Relationship between carbohydrate-induced hypertriglyceridemia and fatty acid synthesis in lean and obese subjects. J Lipid Res. 2000. 41:595-604. | Intervention/exposure
424 | Huerta, S, Li, Z, Li, HC, Hu, MS, Yu, CA, Heber, D. Feasibility of a partial meal replacement plan for weight loss in low-income patients. Int J Obes Relat Metab Disord. 2004. 28:1575-9. doi:10.1038/sj.ijo.0802792. | Study design; Health status
425 | Hughes, LA, Arts, IC, Ambergen, T, Brants, HA, Dagnelie, PC, Goldbohm, RA, van den Brandt, PA, Weijenberg, MP. Higher dietary flavone, flavonol, and catechin intakes are associated with less of an increase in BMI over time in women: a longitudinal analysis from the Netherlands Cohort Study. Am J Clin Nutr. 2008. 88:1341-52. doi:10.3945/ajcn.2008.26058. | Intervention/exposure
426 | Hur, YI, Park, H, Kang, JH, Lee, HA, Song, HJ, Lee, HJ, Kim, OH. Associations between Sugar Intake from Different Food Sources and Adiposity or Cardio-Metabolic Risk in Childhood and Adolescence: The Korean Child-Adolescent Cohort Study. Nutrients. 2015. 8. doi:10.3390/nu8010020. | Intervention/exposure
427 | Hursel, R, Westerterp-Plantenga, M. Effects of simultaneous supplementation of green tea and protein on energy balance. Annals of nutrition and metabolism.. 2011. 58:32. doi:10.1159/000334393. | Publication status
428 | Hursel, R, Westerterp-Plantenga, MS. Green tea catechin plus caffeine supplementation to a high-protein diet has no additional effect on body weight maintenance after weight loss. Am J Clin Nutr. 2009. 89:822-30. doi:10.3945/ajcn.2008.27043. | Intervention/exposure
429 | I’Allemand-Jander, D, Miller, P, Laimbacher, J. Effects of highly mineralized water on weight and metabolism - A randomized controlled blinded trial in a pediatric hospital staff. Hormone research in paediatrics. 2016. 86:327-. doi:10.1159/000449142. | Publication status
430 | Ibrahim, DA. Evaluation of the efficacy of daily consumption of Eucommia ulmoides leaves in a sample of healthy volunteers. Asian Journal of Pharmaceutics. 2018. 12:S591-S596. | Country
431 | Icken, D, Feller, S, Engeli, S, Mayr, A, Muller, A, Hilbert, A, de Zwaan, M. Caffeine intake is related to successful weight loss maintenance. Eur J Clin Nutr. 2016. 70:532-4. doi:10.1038/ejcn.2015.183. | Study design
432 | Ide, K, Takeuchi, M, Seki, T, Kawakami, K. Effect of Regular Exercise and Functional Beverages on Changes in Body Weight and Waist Circumference in Healthy Japanese Subjects. Medicina (Kaunas). 2018. 54. doi:10.3390/medicina54040064. | Intervention/exposure
433 | Igwe, EO, Charlton, KE, Roodenrys, S, Kent, K, Fanning, K, Netzel, ME. Anthocyanin-rich plum juice reduces ambulatory blood pressure but not acute cognitive function in younger and older adults: a pilot crossover dose-timing study. Nutr Res. 2017. 47:28-43. doi:10.1016/j.nutres.2017.08.006. | Outcome
434 | Ilich, JZ, Cvijetic, S, Baric, IC, Cecic, I, Saric, M, Crncevic-Orlic, Z, Blanusa, M, Korsic, M. Nutrition and lifestyle in relation to bone health and body weight in Croatian postmenopausal women. Int J Food Sci Nutr. 2009. 60:319-32. doi:10.1080/09637480701780724. | Study design
435 | Increased coffee consumption could protect against Parkinson disease. Nature Clinical Practice Endocrinology and Metabolism. 2008. 4:534. doi:10.1038/ncpendmet0937. | Study design; Publication status
436 | Inoue, M, Toyokawa, S, Inoue, K, Suyama, Y, Miyano, Y, Suzuki, T, Miyoshi, Y, Kobayashi, Y. Lifestyle, weight perception and change in body mass index of Japanese workers: MY Health Up Study. Public Health. 2010. 124:530-7. doi:10.1016/j.puhe.2010.04.009. | Publication date (SSB published before 2012)
437 | Ishida, N, Iizuka, M, Kataoka, K, Okazaki, M, Shiraishi, K, Yagi, Y, Jobu, K, Yokota, J, Oishi, M, Moriyama, H, Shimamura, T, Matsumura, Y, Ukeda, H, Miyamura, M. Improvement of blood lipid profiles by Goishi tea polyphenols in a randomised, double-blind, placebo-controlled clinical study. Int J Food Sci Nutr. 2018. 69:598-607. doi:10.1080/09637486.2017.1386629. | Outcome
438 | Ishikura, Y, Fujii, W, Sakakibara, Y, Kitogo, T, Katagiri, Y, Oki, M. Safety evaluation of excessive intake of the drink containing Japanese pagoda tree polyphenol (enzymatically modified isoquercitrin) in healthy adults include obesity persons. Japanese pharmacology and therapeutics. 2008. 36:931-939. | Language
439 | Ishikura, Y, Tanaka, Y, Fujii, W, Sakakibara, Y, Sakano, K, Hayashi, M, Ebihara, S. Safety evaluation of excessive intake of the carbonated beverage containing resistant maltodextrin in healthy adults include the volunteers with mild hypertrigryceridemia. Japanese pharmacology and therapeutics. 2011. 39:823-831. | Language
440 | Iso, H, Date, C, Wakai, K, Fukui, M, Tamakoshi, A. The relationship between green tea and total caffeine intake and risk for self-reported type 2 diabetes among Japanese adults. Ann Intern Med. 2006. 144:554-62. doi:10.7326/0003-4819-144-8-200604180-00005. | Outcome
441 | Jackson, SL, Cunningham, SA. The stability of children’s weight status over time, and the role of television, physical activity, and diet. Prev Med. 2017. 100:229-234. doi:10.1016/j.ypmed.2017.04.026. | Intervention/exposure
442 | Jakse, B, Jakse, B, Pajek, J, Pajek, M. Effects of ad libitum consumed, low-fat, high-fiber plant-based diet supplemented with plant-based meal replacements on cardiovascular risk factors. Food Nutr Res. 2019. 63. doi:10.29219/fnr.v63.1560. | Intervention/exposure
443 | Jakse, B, Pinter, S, Jakse, B, Bucar Pajek, M, Pajek, J. Effects of an Ad Libitum Consumed Low-Fat Plant-Based Diet Supplemented with Plant-Based Meal Replacements on Body Composition Indices. Biomed Res Int. 2017. 2017:9626390. doi:10.1155/2017/9626390. | Intervention/exposure
444 | James, J, Thomas, P, Cavan, D, Kerr, D. Preventing childhood obesity by reducing consumption of carbonated drinks: cluster randomised controlled trial. Bmj. 2004. 328:1237. doi:10.1136/bmj.38077.458438.EE. | Intervention/exposure
445 | Jensen, GS, Beaman, JL, He, Y, Guo, Z, Sun, H. Reduction of body fat and improved lipid profile associated with daily consumption of a Puer tea extract in a hyperlipidemic population: a randomized placebo-controlled trial. Clin Interv Aging. 2016. 11:367-76. doi:10.2147/cia.S94881. | Comparator
446 | Jo, G, Kwak, S, Cho, Y, Shin, MJ. Soft drink consumption increases the risk of hypertension in Korean adults: a prospective cohort study. Circulation. 2017. 135. | Publication status
447 | Johansson, I, Esberg, A, Nilsson, LM, Jansson, JH, Wennberg, P, Winkvist, A. Dairy product intake and cardiometabolic diseases in Northern Sweden: A 33-year prospective cohort study. Nutrients. 2019. 11. doi:10.3390/nu11020284. | Outcome
448 | John St, M, Durant, M, Campagna, PD, Rehman, LA, Thompson, AM, Wadsworth, LA, Murphy, RJL. Overweight Nova Scotia children and youth: The roles of household income and adherence to Canada’s food guide to health eating. Canadian Journal of Public Health. 2008. 99:301-306. | Study design
449 | Johnson, L, Mander, AP, Jones, LR, Emmett, PM, Jebb, SA. Is sugar-sweetened beverage consumption associated with increased fatness in children?. Nutrition. 2007. 23:557-63. doi:10.1016/j.nut.2007.05.005. | Publication date
450 | Johnson, LK, Holven, KB, Nordstrand, N, Mellembakken, JR, Tanbo, T, Hjelmesaeth, J. Fructose content of low calorie diets: effect on cardiometabolic risk factors in obese women with polycystic ovarian syndrome: a randomized controlled trial. Endocr Connect. 2015. 4:144-54. doi:10.1530/ec-15-0047. | Intervention/exposure; Health status
451 | Johnson, LKJ, Tanbo, TT, Holven, KBH, Hjelmesæth, JH. Effects of low calorie diets based on crisp bread or liquid meal replacements on metabolic syndrome in morbidly obese women with polycystic ovarian syndrome (PCOS). A randomised controlled trial. Obesity facts. 2013. 6:122-. | Publication status
452 | Josse, AR, Atkinson, SA, Tarnopolsky, MA, Phillips, SM. Increased consumption of dairy foods and protein during diet- and exercise-induced weight loss promotes fat mass loss and lean mass gain in overweight and obese premenopausal women. J Nutr. 2011. 141:1626-34. doi:10.3945/jn.111.141028. | Intervention/exposure
453 | Josse, AR, Tang, JE, Tarnopolsky, MA, Phillips, SM. Body composition and strength changes in women with milk and resistance exercise. Med Sci Sports Exerc. 2010. 42:1122-30. doi:10.1249/MSS.0b013e3181c854f6. | Comparator
454 | Joy, JM, Lowery, RP, Wilson, JM, Purpura, M, De Souza, EO, Wilson, SM, Kalman, DS, Dudeck, JE, Jager, R. The effects of 8 weeks of whey or rice protein supplementation on body composition and exercise performance. Nutr J. 2013. 12:86. doi:10.1186/1475-2891-12-86. | Comparator
455 | Junchi, N, Makiko, Y, Masaaki, U, Nobuyuki, F. Quercetin glucoside-enriched beverage reduced body fat in obese human. Obesity facts. 2014. 7:91. doi:10.1159/000363668. | Publication status
456 | Juturu, V, Wilson, D, Evans, M, Kasper, K, Roderick, R, Khoo, C. Effect of a cranberry beverage on insulinotropic response in moderately hypercholesterolemic overweight/obese adults: a randomized, Double-blind, Placebo-controlled clinical trial. Endocrine practice. 2011. 17:19A. | Publication status
457 | Kadooka, Y, Sato, M, Imaizumi, K, Ogawa, A, Ikuyama, K, Akai, Y, Okano, M, Kagoshima, M, Tsuchida, T. Regulation of abdominal adiposity by probiotics (Lactobacillus gasseri SBT2055) in adults with obese tendencies in a randomized controlled trial. Eur J Clin Nutr. 2010. 64:636-43. doi:10.1038/ejcn.2010.19. | Intervention/exposure; Comparator
458 | Kadooka, Y, Sato, M, Ogawa, A, Miyoshi, M, Uenishi, H, Ogawa, H, Ikuyama, K, Kagoshima, M, Tsuchida, T. Effect of Lactobacillus gasseri SBT2055 in fermented milk on abdominal adiposity in adults in a randomised controlled trial. Br J Nutr. 2013. 110:1696-703. doi:10.1017/s0007114513001037. | Intervention/exposure; Comparator
459 | Kafeshani, M, Entezari, MH, Karimian, J, Pourmasoumi, M, Maracy, MR, Amini, MR, Hadi, A. A comparative study of the effect of green tea and sour tea on blood pressure and lipid profile in healthy adult men. ARYA Atherosclerosis. 2017. 13:109-116. | Intervention/exposure
460 | Kahathuduwa, CN, Davis, T, O’Boyle, M, Boyd, LA, Chin, SH, Paniukov, D, Binks, M. Effects of 3-week total meal replacement vs. typical food-based diet on human brain functional magnetic resonance imaging food-cue reactivity and functional connectivity in people with obesity. Appetite. 2018. 120:431-441. doi:10.1016/j.appet.2017.09.025. | Health status
461 | Kajimoto, O, Kajimoto, Y, Yabune, M, Nakamura, T, Kotani, K, Suzuki, Y, Nozawa, A, Nagata, K, Unno, T, Yuko, MS, Kakuda, T, Yoshikawa, T. Tea catechins with a galloyl moiety reduce body weight and fat. Journal of Health Science. 2005. 51:161-171. doi:10.1248/jhs.51.161. | Comparator
462 | Kalam, F, Kroeger, CM, Trepanowski, JF, Gabel, K, Song, JH, Cienfuegos, S, Varady, KA. Beverage intake during alternate-day fasting: Relationship to energy intake and body weight. Nutr Health. 2019. 260106019841452. doi:10.1177/0260106019841452. | Study design; Intervention/exposure
463 | Kalman, D, Feldman, S, Martinez, M, Krieger, DR, Tallon, MJ. Effect of protein source and resistance training on body composition and sex hormones. J Int Soc Sports Nutr. 2007. 4:4. doi:10.1186/1550-2783-4-4. | Intervention/exposure; Comparator
464 | Kamphuis, PJGH, Verhey, FRJ, Olde Rikkert, MGM, Twisk, JWR, Swinkels, SHN, Scheltens, P. Effect of a medical food on body mass index and activities of daily living in patients with Alzheimer’s disease: Secondary analyses from a randomized, controlled trial. Journal of Nutrition, Health and Aging. 2011. 15:672-676. doi:10.1007/s12603-011-0339-3. | Comparator; Health status
465 | Kamycheva, E, Joakimsen, RM, Jorde, R. Intakes of calcium and vitamin d predict body mass index in the population of Northern Norway. J Nutr. 2003. 133:102-6. doi:10.1093/jn/133.1.102. | Study design
466 | Kant, AK, Graubard, BI. A comparison of three dietary pattern indexes for predicting biomarkers of diet and disease. J Am Coll Nutr. 2005. 24:294-303. | Study design; Intervention/exposure
467 | Karabudak, E, Kiziltan, G. The relationship between caloric beverage consumption and body mass index in Turkish university students. Pakistan Journal of Nutrition. 2008. 7:202-207. doi:10.3923/pjn.2008.202.207. | Study design; Country
468 | Karadavut, B, Şahin, H, Kaner, G, Karadavut, S. Is beverage consumption associated with increased body weight among adolescents?. Progress in Nutrition. 2017. 19:41-47. doi:10.23751/pn.v19i1.5133. | Study design
469 | Karelis, AD, Messier, V, Suppere, C, Briand, P, Rabasa-Lhoret, R. Effect of cysteine-rich whey protein (immunocal(R)) supplementation in combination with resistance training on muscle strength and lean body mass in non-frail elderly subjects: a randomized, double-blind controlled study. J Nutr Health Aging. 2015. 19:531-6. doi:10.1007/s12603-015-0442-y. | Intervention/exposure; Comparator
470 | Karkkainen, U, Mustelin, L, Raevuori, A, Kaprio, J, Keski-Rahkonen, A. Successful weight maintainers among young adults-A ten-year prospective population study. Eat Behav. 2018. 29:91-98. doi:10.1016/j.eatbeh.2018.03.004. | Duplicate
471 | Kaufman, F. Back away from the soda! Nearly half of all children between the ages of 6 and 11 drink sweetened sodas. Are these sugar-laden beverages partly to blame for the obesity epidemic?. Diabetes Forecast. 2005. 58:42-5. | Publication status
472 | Kavey, RE. How sweet it is: sugar-sweetened beverage consumption, obesity, and cardiovascular risk in childhood. J Am Diet Assoc. 2010. 110:1456-60. doi:10.1016/j.jada.2010.07.028. | Study design
473 | Kawano, Y, Ishizaki, S, Sasamoto, S, Katoh, Y, Kobayashi, S. Effect of meals with milk on body iron stores and improvement of dietary habit during weight loss in female rhythmic gymnasts. J Nutr Sci Vitaminol (Tokyo). 2002. 48:395-400. | Intervention/exposure; Comparator
474 | Kemmler, W, Grimm, A, Bebenek, M, Kohl, M, von Stengel, S. Effects of Combined Whole-Body Electromyostimulation and Protein Supplementation on Local and Overall Muscle/Fat Distribution in Older Men with Sarcopenic Obesity: The Randomized Controlled Franconia Sarcopenic Obesity (FranSO) Study. Calcif Tissue Int. 2018. 103:266-277. doi:10.1007/s00223-018-0424-2. | Intervention/exposure; Health status
475 | Kempf, K, Kolb, H, Gartner, B, Bytof, G, Stiebitz, H, Lantz, I, Lang, R, Hofmann, T, Martin, S. Cardiometabolic effects of two coffee blends differing in content for major constituents in overweight adults: a randomized controlled trial. Eur J Nutr. 2015. 54:845-54. doi:10.1007/s00394-014-0763-3. | Comparator
476 | Keogh, JB, Clifton, P. The effect of meal replacements high in glycomacropeptide on weight loss and markers of cardiovascular disease risk. Am J Clin Nutr. 2008. 87:1602-5. doi:10.1093/ajcn/87.6.1602. | Comparator
477 | Kerrigan, DJ, Rukstalis, MR, Ehrman, JK, Keteyian, SJ, She, R, Alexander, GL. 5-2-1-0 Lifestyle risk factors predict obesity in Millennials. Clin Obes. 2019. 9:e12306. doi:10.1111/cob.12306. | Study design
478 | Kerstetter, JE, Bihuniak, JD, Brindisi, J, Sullivan, RR, Mangano, KM, Larocque, S, Kotler, BM, Simpson, CA, Cusano, AM, Gaffney-Stomberg, E, Kleppinger, A, Reynolds, J, Dziura, J, Kenny, AM, Insogna, KL. The Effect of a Whey Protein Supplement on Bone Mass in Older Caucasian Adults. J Clin Endocrinol Metab. 2015. 100:2214-22. doi:10.1210/jc.2014-3792. | Intervention/exposure
479 | Khalili, H, Hakansson, N, Chan, SS, Ludvigsson, JF, Olen, O, Chan, AT, Hart, AR, Wolk, A. No Association Between Consumption of Sweetened Beverages and Risk of Later-Onset Crohn’s Disease or Ulcerative Colitis. Clin Gastroenterol Hepatol. 2019. 17:123-129. doi:10.1016/j.cgh.2018.04.059. | Outcome
480 | Khalsa, AS, Kharofa, R, Ollberding, NJ, Bishop, L, Copeland, KA. Attainment of ‘5-2-1-0’ obesity recommendations in preschool-aged children. Prev Med Rep. 2017. 8:79-87. doi:10.1016/j.pmedr.2017.08.003. | Study design
481 | Khoo, J, Chen, R, Tan, E, Tay, TL, Cho, L, Au, V, Soh, SB, Ng, B. Comparing effects of a partial meal replacement diet plan with conventional diet on weight loss, insulin resistance, lipids, sexual and endothelial function, and urinary tract symptoms in obese men. Obesity facts.. 2012. 5:219. doi:10.1159/000207438. | Publication status
482 | Khoo, J, Chen, RYT, Cheong, M, Ling, PS, Ng, KK. Comparing effects of meal replacements with isocaloric diet plan on voiding and storage lower urinary tract symptoms, insulin resistance and nutrient intake in obese men. Obesity facts.. 2013. 6:103-104. | Publication status
483 | Khoo, J, Ling, PS, Chen, RY, Ng, KK, Tay, TL, Tan, E, Cho, LW, Cheong, M. Comparing the effects of meal replacements with an isocaloric reduced-fat diet on nutrient intake and lower urinary tract symptoms in obese men. J Hum Nutr Diet. 2014. 27:219-26. doi:10.1111/jhn.12151. | Health status
484 | Khoo, J, Ling, PS, Tan, J, Teo, A, Ng, HL, Chen, RY, Tay, TL, Tan, E, Cheong, M. Comparing the effects of meal replacements with reduced-fat diet on weight, sexual and endothelial function, testosterone and quality of life in obese Asian men. Int J Impot Res. 2014. 26:61-6. doi:10.1038/ijir.2013.36. | Health status; Duplicate
485 | Khoo, J, Ling, PS, Tan, J, Teo, A, Ng, HL, Chen, RYT, Tay, TL, Tan, E, Cheong, M. Comparing the effects of meal replacements with reduced-fat diet on weight, sexual and endothelial function, testosterone and quality of life in obese Asian men. International Journal of Impotence Research. 2013. 26:61-66. doi:10.1038/ijir.2013.36. | Health status
486 | Khoo, J, Ling, PS, Yap, SY, Chen, DD, Dhamodaran, S. Comparing effects of a partial meal replacement diet plan with conventional diet on weight loss, fat mass, chemerin, insulin and peptide YY levels, and inflammation in obese men. Obesity facts.. 2015. 8:70. doi:10.1159/000382140. | Publication status
487 | Khoo, J, Piantadosi, C, Duncan, R, Worthley, SG, Jenkins, A, Noakes, M, Worthley, MI, Lange, K, Wittert, GA. Comparing effects of a low-energy diet and a high-protein low-fat diet on sexual and endothelial function, urinary tract symptoms, and inflammation in obese diabetic men. J Sex Med. 2011. 8:2868-75. doi:10.1111/j.1743-6109.2011.02417.x. | Health status
488 | Kim, H, Kim, M, Kojima, N, Fujino, K, Hosoi, E, Kobayashi, H, Somekawa, S, Niki, Y, Yamashiro, Y, Yoshida, H. Exercise and Nutritional Supplementation on Community-Dwelling Elderly Japanese Women With Sarcopenic Obesity: A Randomized Controlled Trial. J Am Med Dir Assoc. 2016. 17:1011-1019. doi:10.1016/j.jamda.2016.06.016. | Intervention/exposure; Comparator
489 | Kim, H, Simbo, SY, Fang, C, McAlister, L, Roque, A, Banerjee, N, Talcott, ST, Zhao, H, Kreider, RB, Mertens-Talcott, SU. Acai (Euterpe oleracea Mart.) beverage consumption improves biomarkers for inflammation but not glucose- or lipid-metabolism in individuals with metabolic syndrome in a randomized, double-blinded, placebo-controlled clinical trial. Food Funct. 2018. 9:3097-3103. doi:10.1039/c8fo00595h. | Comparator
490 | Kim, H, Simbo, SY, Fang, C, McAlister, L, Roque, A, Banerjee, N, Talcott, ST, Zhao, H, Kreider, RB, Mertens-Talcott, SU. Açaí (Euterpe oleracea Mart.) beverage consumption improves biomarkers for inflammation but not glucose- or lipid-metabolism in individuals with metabolic syndrome in a randomized, double-blinded, placebo-controlled clinical trial. Food & function. 2018. 9:3097-3103. doi:10.1039/c8fo00595h. | Duplicate
491 | Kim, H, Suzuki, T, Saito, K, Yoshida, H, Kojima, N, Kim, M, Sudo, M, Yamashiro, Y, Tokimitsu, I. Effects of exercise and tea catechins on muscle mass, strength and walking ability in community-dwelling elderly Japanese sarcopenic women: a randomized controlled trial. Geriatr Gerontol Int. 2013. 13:458-65. doi:10.1111/j.1447-0594.2012.00923.x. | Intervention/exposure
492 | Kim, HM, Kim, J. The effects of green tea on obesity and type 2 diabetes. Diabetes Metab J. 2013. 37:173-5. doi:10.4093/dmj.2013.37.3.173. | Study design; Publication status
493 | Kim, J, Yun, JM, Kim, MK, Kwon, O, Cho, B. Lactobacillus gasseri BNR17 Supplementation Reduces the Visceral Fat Accumulation and Waist Circumference in Obese Adults: A Randomized, Double-Blind, Placebo-Controlled Trial. J Med Food. 2018. 21:454-461. doi:10.1089/jmf.2017.3937. | Intervention/exposure
494 | Kim, MJ, Hwang, JH, Ko, HJ, Na, HB, Kim, JH. Lemon detox diet reduced body fat, insulin resistance, and serum hs-CRP level without hematological changes in overweight Korean women. Nutr Res. 2015. 35:409-20. doi:10.1016/j.nutres.2015.04.001. | Intervention/exposure; Comparator
495 | Kim, SY, Lee, YJ. Seasonal and gender differences of beverage consumption in elementary school students. Nutr Res Pract. 2009. 3:234-41. doi:10.4162/nrp.2009.3.3.234. | Study design
496 | Kim, SY, Yoon, S, Kwon, SM, Park, KS, Lee-Kim, YC. Kale juice improves coronary artery disease risk factors in hypercholesterolemic men. Biomed Environ Sci. 2008. 21:91-7. doi:10.1016/s0895-3988(08)60012-4. | Study design
497 | Kimble, L, Mathison, B, McKay, D, Chen, Yo C, Blumberg, J, Kaspar, K, Khoo, C, Chew, B. Chronic consumption of a high polyphenol cranberry beverage protects against inflammation and improves endothelial function in healthy but overweight humans. FASEB journal. 2014. 28. | Publication status
498 | Kjolbaek, L, Sorensen, LB, Sondertoft, NB, Rasmussen, CK, Lorenzen, JK, Serena, A, Astrup, A, Larsen, LH. Protein supplements after weight loss do not improve weight maintenance compared with recommended dietary protein intake despite beneficial effects on appetite sensation and energy expenditure: a randomized, controlled, double-blinded trial. Am J Clin Nutr. 2017. 106:684-697. doi:10.3945/ajcn.115.129528. | Comparator
499 | Klesges, RC, Obarzanek, E, Kumanyika, S, Murray, DM, Klesges, LM, Relyea, GE, Stockton, MB, Lanctot, JQ, Beech, BM, McClanahan, BS, Sherrill-Mittleman, D, Slawson, DL. The Memphis Girls’ health Enrichment Multi-site Studies (GEMS): an evaluation of the efficacy of a 2-year obesity prevention program in African American girls. Arch Pediatr Adolesc Med. 2010. 164:1007-14. doi:10.1001/archpediatrics.2010.196. | Intervention/exposure
500 | Ko, GTC, Chan, JCN, Tong, SDY, Chan, AWY, Wong, PTS, Hui, SSC, Kwok, R, Chan, CLW. Associations between dietary habits and risk factors for cardiovascular diseases in a Hong Kong Chinese working population - The “Better Health for Better Hong Kong” (BHBHK) health promotion campaign. Asia Pacific Journal of Clinical Nutrition. 2007. 16:757-765. | Study design
501 | Kobayashi, M, Kawano, T, Ukawa, Y, Sagesaka, YM, Fukuhara, I. Green tea beverages enriched with catechins with a galloyl moiety reduce body fat in moderately obese adults: a randomized double-blind placebo-controlled trial. Food Funct. 2016. 7:498-507. doi:10.1039/c5fo00750j. | Comparator
502 | Koga, R, Tanaka, M, Tsuda, H, Imai, K, Abe, S, Masuda, T, Iwamoto, M, Nakazono, E, Kamohara, T, Sakata, T. Daily exercise fluctuations and dietary patterns during training predict visceral fat regain in obese women. Am J Med Sci. 2008. 336:450-7. doi:10.1097/MAJ.0b013e31817242a5. | Intervention/exposure
503 | Kok, L, Kreijkamp-Kaspers, S, Grobbee, DE, Lampe, JW, van der Schouw, YT. Soy isoflavones, body composition, and physical performance. Maturitas. 2005. 52:102-10. doi:10.1016/j.maturitas.2005.01.003. | Intervention/exposure
504 | Koloverou, E, Panagiotakos, DB, Pitsavos, C, Chrysohoou, C, Georgousopoulou, EN, Laskaris, A, Stefanadis, C. The evaluation of inflammatory and oxidative stress biomarkers on coffee-diabetes association: Results from the 10-year follow-up of the ATTICA Study (2002-2012). European Journal of Clinical Nutrition. 2015. 69:1220-1225. doi:10.1038/ejcn.2015.98. | Outcome
505 | Konig, D, Deibert, P, Frey, I, Landmann, U, Berg, A. Effect of meal replacement on metabolic risk factors in overweight and obese subjects. Ann Nutr Metab. 2008. 52:74-8. doi:10.1159/000119416. | Intervention/exposure
506 | Konig, D, Kookhan, S, Schaffner, D, Deibert, P, Berg, A. A meal replacement regimen improves blood glucose levels in prediabetic healthy individuals with impaired fasting glucose. Nutrition. 2014. 30:1306-9. doi:10.1016/j.nut.2014.03.014. | Intervention/exposure; Comparator
507 | Konig, D, Zdzieblik, D, Deibert, P, Berg, A, Gollhofer, A, Buchert, M. Internal Fat and Cardiometabolic Risk Factors Following a Meal-Replacement Regimen vs. Comprehensive Lifestyle Changes in Obese Subjects. Nutrients. 2015. 7:9825-33. doi:10.3390/nu7125500. | Intervention/exposure; Health status
508 | Koohkan, S, Schaffner, D, Milliron, BJ, Frey, I, Konig, D, Deibert, P, Vitolins, M, Berg, A. The impact of a weight reduction program with and without meal-replacement on health related quality of life in middle-aged obese females. BMC Womens Health. 2014. 14:45. doi:10.1186/1472-6874-14-45. | Health status
509 | Korpelainen, R, Korpelainen, J, Heikkinen, J, Vaananen, K, Keinanen-Kiukaanniemi, S. Lifestyle factors are associated with osteoporosis in lean women but not in normal and overweight women: a population-based cohort study of 1222 women. Osteoporos Int. 2003. 14:34-43. doi:10.1007/s00198-002-1319-6. | Outcome
510 | Kouli, GM, Panagiotakos, DB, Georgousopoulou, EN, Mellor, DD, Chrysohoou, C, Zana, A, Tsigos, C, Tousoulis, D, Stefanadis, C, Pitsavos, C. J-shaped relationship between habitual coffee consumption and 10-year (2002–2012) cardiovascular disease incidence: the ATTICA study. European Journal of Nutrition. 2018. 57:1677-1685. doi:10.1007/s00394-017-1455-6. | Outcome
511 | Kovacs, E, Hunsberger, M, Reisch, L, Gwozdz, W, Eiben, G, De Bourdeaudhuij, I, Russo, P, Veidebaum, T, Hadjigeorgiou, C, Sieri, S, Moreno, LA, Pigeot, I, Ahrens, W, Pohlabeln, H, Molnar, D. Adherence to combined lifestyle factors and their contribution to obesity in the IDEFICS study. Obes Rev. 2015. 16 Suppl 2:138-50. doi:10.1111/obr.12349. | Study design
512 | Kovacs, EM, Lejeune, MP, Nijs, I, Westerterp-Plantenga, MS. Effects of green tea on weight maintenance after body-weight loss. Br J Nutr. 2004. 91:431-7. doi:10.1079/bjn20041061. | Intervention/exposure
513 | Kozuma, K, Chikama, A, Hishino, E, Kataoka, K, Mori, K, Hase, T. Effect of intake of a beverage containing 540 mg catechins on the body composition of obese women and men. Progress in medicine. 2005. 25:185-197. | Language
514 | Krebs, JD, Evans, S, Cooney, L, Mishra, GD, Fruhbeck, G, Finer, N, Jebb, SA. Changes in risk factors for cardiovascular disease with body fat loss in obese women. Diabetes Obes Metab. 2002. 4:379-87. | Study design; Intervention/exposure
515 | Kreider, RB, Serra, M, Beavers, KM, Moreillon, J, Kresta, JY, Byrd, M, Oliver, JM, Gutierrez, J, Hudson, G, Deike, E, Shelmadine, B, Leeke, P, Rasmussen, C, Greenwood, M, Cooke, MB, Kerksick, C, Campbell, JK, Beiseigel, J, Jonnalagadda, SS. A structured diet and exercise program promotes favorable changes in weight loss, body composition, and weight maintenance. J Am Diet Assoc. 2011. 111:828-43. doi:10.1016/j.jada.2011.03.013. | Intervention/exposure
516 | Kruger, MC, Chan, YM, Kuhn-Sherlock, B, Lau, LT, Lau, C, Chin, YS, Todd, JM, Schollum, LM. Differential effects of calcium- and vitamin D-fortified milk with FOS-inulin compared to regular milk, on bone biomarkers in Chinese pre- and postmenopausal women. Eur J Nutr. 2016. 55:1911-21. doi:10.1007/s00394-015-1007-x. | Outcome
517 | Kruger, MC, Chan, YM, Kuhn-Sherlock, B, Lau, LT, Lau, CC, Chin, YS, Todd, J, Schollum, L. Calcium and vitamin D fortified milk reduces bone turnover and improves bone density in postmenopausal women over one year. Osteoporosis international. 2016. 27:S774-. doi:10.1007/s00198-016-3748-7. | Publication status
518 | Kruger, MC, Chan, YM, Lau, C, Lau, LT, Chin, YS, Kuhn-Sherlock, B, Schollum, LM, Todd, JM. Fortified Milk Supplementation Improves Vitamin D Status, Grip Strength, and Maintains Bone Density in Chinese Premenopausal Women Living in Malaysia. Biores Open Access. 2019. 8:16-24. doi:10.1089/biores.2018.0027. | Comparator
519 | Kruger, MC, Chan, YM, Lau, LT, Lau, CC, Chin, YS, Kuhn-Sherlock, B, Todd, JM, Schollum, LM. Calcium and vitamin D fortified milk reduces bone turnover and improves bone density in postmenopausal women over 1 year. Eur J Nutr. 2018. 57:2785-2794. doi:10.1007/s00394-017-1544-6. | Outcome
520 | Kubota, K, Sumi, S, Tojo, H, Sumi-Inoue, Y, Chin H I, Oi, Y, Fujita, H, Urata, H. Improvements of mean body mass index and body weight in preobese and overweight Japanese adults with black Chinese tea (Pu-Erh) water extract. Nutr Res. 2011. 31:421-8. doi:10.1016/j.nutres.2011.05.004. | Comparator
521 | Kuhl, ES, Clifford, LM, Bandstra, NF, Filigno, SS, Yeomans-Maldonado, G, Rausch, JR, Stark, LJ. Examination of the association between lifestyle behavior changes and weight outcomes in preschoolers receiving treatment for obesity. Health Psychol. 2014. 33:95-8. doi:10.1037/a0032741. | Health status
522 | Kukuljan, S, Nowson, CA, Bass, SL, Sanders, K, Nicholson, GC, Seibel, MJ, Salmon, J, Daly, RM. Effects of a multi-component exercise program and calcium-vitamin-D3-fortified milk on bone mineral density in older men: a randomised controlled trial. Osteoporos Int. 2009. 20:1241-51. doi:10.1007/s00198-008-0776-y. | Intervention/exposure; Other (e.g., duplicative data)
523 | Kukuljan, S, Nowson, CA, Sanders, K, Daly, RM. Effects of resistance exercise and fortified milk on skeletal muscle mass, muscle size, and functional performance in middle-aged and older men: an 18-mo randomized controlled trial. J Appl Physiol (1985). 2009. 107:1864-73. doi:10.1152/japplphysiol.00392.2009. | Intervention/exposure
524 | Kumao, T, Fujii, S, Takehara, I, Fukuhara, I. Effect of long-term ingestion of milk added liquid coffee containing mannooligosaccharides on human body fat. Japanese pharmacology and therapeutics. 2008. 36:541-548. | Comparator; Language
525 | Kumao, T, Fujii, S, Takehara, I, Fukuhara, I. Effect of soluble coffee containing mannooligosaccharides on human body fat by long-term ingestion. Japanese pharmacology and therapeutics. 2007. 35:673-679. | Comparator; Language
526 | Kumar, NB, Patel, R, Pow-Sang, J, Spiess, PE, Salup, R, Williams, CR, Schell, MJ. Long-term supplementation of decaffeinated green tea extract does not modify body weight or abdominal obesity in a randomized trial of men at high risk for prostate cancer. Oncotarget. 2017. 8:99093-99103. doi:10.18632/oncotarget.18858. | Intervention/exposure
527 | Kuno, K, Kojima, Y, Kai, K, Sakemoto, S, Tsuji, M, Kuno, T. Influence of supplemental drinks on dietary intake, body composition and biochemical data in the community-healthy elderly. Japanese pharmacology and therapeutics. 2014. 42:281-287. | Language
528 | Kuperberg, K, Evers, S. Feeding patterns and weight among First Nations children. Can J Diet Pract Res. 2006. 67:79-84. doi:10.3148/67.2.2006.79. | Study design; Intervention/exposure
529 | Kuzma, JN, Cromer, G, Hagman, DK, Breymeyer, KL, Roth, CL, Foster-Schubert, KE, Holte, SE, Weigle, DS, Kratz, M. No differential effect of beverages sweetened with fructose, high-fructose corn syrup, or glucose on systemic or adipose tissue inflammation in normal-weight to obese adults: a randomized controlled trial. Am J Clin Nutr. 2016. 104:306-14. doi:10.3945/ajcn.115.129650. | Comparator
530 | Kvaavik, E, Andersen, LF, Klepp, KI. The stability of soft drinks intake from adolescence to adult age and the association between long-term consumption of soft drinks and lifestyle factors and body weight. Public Health Nutr. 2005. 8:149-57. | Publication date
531 | Lam, BCC, Han, JSY, Ho, CY, Teoh, H, Yum, MPS, Wong, MTK, Koh, GCH. The effect of intermittent energy restriction using meal replacements in overweight chinese subjects: a pilot randomized control trial. Obesity facts. 2018. 11:307-. doi:10.1159/000489691. | Publication status
532 | Lampard, AM, Maclehose, RF, Eisenberg, ME, Larson, NI, Davison, KK, Neumark-Sztainer, D. Adolescents who engage exclusively in healthy weight control behaviors: Who are they?. Int J Behav Nutr Phys Act. 2016. 13:5. doi:10.1186/s12966-016-0328-3. | Study design; Outcome
533 | Lana, A, Lopez-Garcia, E, Rodríguez-Artalejo, F. Consumption of soft drinks and health-related quality of life in the adult population. European Journal of Clinical Nutrition. 2015. 69:1226-1232. doi:10.1038/ejcn.2015.103. | Outcome
534 | Langsetmo, L, Hanley, DA, Prior, JC, Barr, SI, Anastassiades, T, Towheed, T, Goltzman, D, Morin, S, Poliquin, S, Kreiger, N. Dietary patterns and incident low-trauma fractures in postmenopausal women and men aged >/= 50 y: a population-based cohort study. Am J Clin Nutr. 2011. 93:192-9. doi:10.3945/ajcn.110.002956. | Intervention/exposure
535 | Langsetmo, L, Poliquin, S, Hanley, DA, Prior, JC, Barr, S, Anastassiades, T, Towheed, T, Goltzman, D, Kreiger, N. Dietary patterns in Canadian men and women ages 25 and older: relationship to demographics, body mass index, and bone mineral density. BMC Musculoskelet Disord. 2010. 11:20. doi:10.1186/1471-2474-11-20. | Intervention/exposure
536 | Lappe, JM, McMahon, DJ, Laughlin, A, Hanson, C, Desmangles, JC, Begley, M, Schwartz, M. The effect of increasing dairy calcium intake of adolescent girls on changes in body fat and weight. Am J Clin Nutr. 2017. 105:1046-1053. doi:10.3945/ajcn.116.138941. | Intervention/exposure; Comparator
537 | Lara, J, Ogbonmwan, I, Oggioni, C, Zheng, D, Mathers, JC, Siervo, M. Isometric handgrip exercise or beetroot juice does not lower blood pressure in overweight older adults: a randomised controlled trial. Proceedings of the nutrition society. 2015. 74. doi:10.1017/S0029665115001469. | Publication status
538 | LaRowe, TL, Adams, AK, Jobe, JB, Cronin, KA, Vannatter, SM, Prince, RJ. Dietary intakes and physical activity among preschool-aged children living in rural American Indian communities before a family-based healthy lifestyle intervention. J Am Diet Assoc. 2010. 110:1049-57. doi:10.1016/j.jada.2010.04.009. | Study design
539 | Larsen, SC, Mikkelsen, ML, Frederiksen, P, Heitmann, BL. Habitual coffee consumption and changes in measures of adiposity: a comprehensive study of longitudinal associations. Int J Obes (Lond). 2018. 42:880-886. doi:10.1038/ijo.2017.310. | Intervention/exposure
540 | Larsson, SC, Virtamo, J, Wolk, A. Coffee consumption and risk of stroke in women. Stroke. 2011. 42:908-12. doi:10.1161/strokeaha.110.603787. | Outcome
541 | Laso, N, Brugue, E, Vidal, J, Ros, E, Arnaiz, JA, Carne, X, Vidal, S, Mas, S, Deulofeu, R, Lafuente, A. Effects of milk supplementation with conjugated linoleic acid (isomers cis-9, trans-11 and trans-10, cis-12) on body composition and metabolic syndrome components. Br J Nutr. 2007. 98:860-7. doi:10.1017/s0007114507750882. | Intervention/exposure
542 | Laverty, AA, Magee, L, Monteiro, CA, Saxena, S, Millett, C. Sugar and artificially sweetened beverage consumption and adiposity changes: National longitudinal study. Int J Behav Nutr Phys Act. 2015. 12:137. doi:10.1186/s12966-015-0297-y. | Study design
543 | Lawlor, DA, Ebrahim, S, Timpson, N, Smith, GD. Avoiding milk is associated with a reduced risk of insulin resistance and the metabolic syndrome: Findings from the British Women’s Heart and Health Study. Diabetic Medicine. 2005. 22:808-811. doi:10.1111/j.1464-5491.2005.01537.x. | Study design
544 | LeCheminant, JD, Jacobsen, DJ, Hall, MA, Donnelly, JE. A comparison of meal replacements and medication in weight maintenance after weight loss. J Am Coll Nutr. 2005. 24:347-53. | Intervention/exposure; Comparator
545 | LeCheminant, JD, Smith, BK, Westman, EC, Vernon, MC, Donnelly, JE. Comparison of a reduced carbohydrate and reduced fat diet for LDL, HDL, and VLDL subclasses during 9-months of weight maintenance subsequent to weight loss. Lipids Health Dis. 2010. 9:54. doi:10.1186/1476-511x-9-54. | Intervention/exposure
546 | LeCroy, MN, Truesdale, KP, Matheson, DM, Karp, SM, Moore, SM, Robinson, TN, Berge, JM, Nicastro, HL, Thomas, AJ. Snacking characteristics and patterns and their associations with diet quality and BMI in the Childhood Obesity Prevention and Treatment Research Consortium. Public Health Nutr. 2019. 1-11. doi:10.1017/s1368980019000958. | Study design
547 | Lee, CY, Lin, WT, Tsai, S, Hung, YC, Wu, PW, Yang, YC, Chan, TF, Huang, HL, Weng, YL, Chiu, YW, Huang, CT, Lee, CH. Association of Parental Overweight and Cardiometabolic Diseases and Pediatric Adiposity and Lifestyle Factors with Cardiovascular Risk Factor Clustering in Adolescents. Nutrients. 2016. 8. doi:10.3390/nu8090567. | Study design
548 | Lee, I, Bang, KS, Moon, H, Kim, J. Risk Factors for Obesity Among Children Aged 24 to 80 months in Korea: A Decision Tree Analysis. J Pediatr Nurs. 2019. 46:e15-e23. doi:10.1016/j.pedn.2019.02.004. | Study design; Population [underlined: at Intervention/exposure]
549 | Lee, K, Lee, J, Bae, WK, Choi, JK, Kim, HJ, Cho, B. Efficacy of low-calorie, partial meal replacement diet plans on weight and abdominal fat in obese subjects with metabolic syndrome: a double-blind, randomised controlled trial of two diet plans - one high in protein and one nutritionally balanced. Int J Clin Pract. 2009. 63:195-201. doi:10.1111/j.1742-1241.2008.01965.x. | Intervention/exposure; Comparator
550 | Lee, KR, Ko, KD, Whang, IC, Kim, KK, Suh, H. Phentermine/topiramate/ephedrine with coffee shows to weight management in obesity for 4 weeks, especially those with high VAT and hyperglycemia. Obesity facts.. 2015. 8:235. doi:10.1159/000382140. | Publication status
551 | Lee, M. Obesogenic environment factors related to the obesity prevalence in Korean children. FASEB journal. 2018. 32. | Publication status
552 | Lee, R. Beverages: The Good, the Bad and the Ugly. Explore: The Journal of Science and Healing. 2008. 4:210-212. doi:10.1016/j.explore.2008.02.012. | Study design
553 | Lee, SK, Novotny, R, Daida, YG, Vijayadeva, V, Gittelsohn, J. Dietary patterns of adolescent girls in Hawaii over a 2-year period. J Am Diet Assoc. 2007. 107:956-61. doi:10.1016/j.jada.2007.03.009. | Outcome
554 | Lee, SM, Kim, S, Lim, CG. The effects of milk intake and whole-body vibration exercise on bone mineral density in elderly women in nursing homes. J Phys Ther Sci. 2017. 29:1125-1128. doi:10.1589/jpts.29.1125. | Intervention/exposure
555 | Lee, YY, Wan Muda, WAM. Dietary intakes and obesity of Malaysian adults. Nutr Res Pract. 2019. 13:159-168. doi:10.4162/nrp.2019.13.2.159. | Study design
556 | Lefort, A. Effects of whey and fortified collagen hydrolysate protein supplements on nitrogen balance and body composition in elderly women. Cahiers de l’annee gerontologique. 2010. 2:205-207. doi:10.1007/s12612-010-0064-2. | Language
557 | Lenhart, CM, Bauer, KW, Patterson, F. Weight status and weight-management behaviors among Philadelphia high school students, 2007-2011. Prev Chronic Dis. 2013. 10:E164. doi:10.5888/pcd10.130087. | Study design; Intervention/exposure
558 | Leroy, JL, Sununtnasuk, C, Garcia-Guerra, A, Wang, JS. Low level aflatoxin exposure associated with greater linear growth in southern Mexico: A longitudinal study. Matern Child Nutr. 2018. 14:e12619. doi:10.1111/mcn.12619. | Intervention/exposure; Population at Intervention/exposure
559 | Levitsky, DA, Pacanowski, C. Losing weight without dieting. Use of commercial foods as meal replacements for lunch produces an extended energy deficit. Appetite. 2011. 57:311-7. doi:10.1016/j.appet.2011.04.015. | Intervention/exposure
560 | Levy, Y, Narotzki, B, Reznick, AZ. Green tea, weight loss and physical activity. Clinical nutrition (edinburgh, scotland). 2017. 36:315. doi:10.1016/j.clnu.2016.11.001. | Study design
561 | Li, J, Wang, Y. Tracking of dietary intake patterns is associated with baseline characteristics of urban low-income African-American adolescents. J Nutr. 2008. 138:94-100. doi:10.1093/jn/138.1.94. | Outcome
562 | Li, S, Guerin-Deremaux, L, Pochat, M, Wils, D, Reifer, C, Miller, LE. NUTRIOSE dietary fiber supplementation improves insulin resistance and determinants of metabolic syndrome in overweight men: a double-blind, randomized, placebo-controlled study. Appl Physiol Nutr Metab. 2010. 35:773-82. doi:10.1139/h10-074. | Intervention/exposure; Country
563 | Li, YF, Chang, YY, Huang, HC, Wu, YC, Yang, MD, Chao, PM. Tomato juice supplementation in young women reduces inflammatory adipokine levels independently of body fat reduction. Nutrition. 2015. 31:691-6. doi:10.1016/j.nut.2014.11.008. | Study design
564 | Li, YH, Gu, ZY. Aerobic exercise combined with long-term drinking of lotus-leaf water can produce better effect on weight reduction. International Journal of Clinical and Experimental Medicine. 2016. 9:22141-22147. | Intervention/exposure
565 | Li, Z, Treyzon, L, Chen, S, Yan, E, Thames, G, Carpenter, CL. Protein-enriched meal replacements do not adversely affect liver, kidney or bone density: an outpatient randomized controlled trial. Nutr J. 2010. 9:72. doi:10.1186/1475-2891-9-72. | Intervention/exposure; Comparator
566 | Libuda, L, Alexy, U, Remer, T, Stehle, P, Schoenau, E, Kersting, M. Association between long-term consumption of soft drinks and variables of bone modeling and remodeling in a sample of healthy German children and adolescents. Am J Clin Nutr. 2008. 88:1670-7. doi:10.3945/ajcn.2008.26414. | Study design; Outcome
567 | Libuda, L, Alexy, U, Sichert-Hellert, W, Stehle, P, Karaolis-Danckert, N, Buyken, AE, Kersting, M. Pattern of beverage consumption and long-term association with body-weight status in German adolescents--results from the DONALD study. Br J Nutr. 2008. 99:1370-9. doi:10.1017/s0007114507862362. | Duplicate
568 | Lim, L, Banwell, C, Bain, C, Banks, E, Seubsman, SA, Kelly, M, Yiengprugsawan, V, Sleigh, A. Sugar sweetened beverages and weight gain over 4 years in a Thai national cohort - A prospective analysis. PLoS ONE. 2014. 9. doi:10.1371/journal.pone.0095309. | Country
569 | Lim, L, Banwell, C, Bain, C, Banks, E, Seubsman, SA, Kelly, M, Yiengprugsawan, V, Sleigh, A. Sugar sweetened beverages and weight gain over 4 years in a Thai national cohort--a prospective analysis. PLoS One. 2014. 9:e95309. doi:10.1371/journal.pone.0095309. | Country; Duplicate
570 | Lim, S, Zoellner, JM, Lee, JM, Burt, BA, Sandretto, AM, Sohn, W, Ismail, AI, Lepkowski, JM. Obesity and sugar-sweetened beverages in African-American preschool children: a longitudinal study. Obesity (Silver Spring). 2009. 17:1262-8. doi:10.1038/oby.2008.656. | Publication date
571 | Lima, ACD, Cecatti, C, Fidelix, MP, Adorno, MAT, Sakamoto, IK, Cesar, TB, Sivieri, K. Effect of Daily Consumption of Orange Juice on the Levels of Blood Glucose, Lipids, and Gut Microbiota Metabolites: Controlled Clinical Trials. J Med Food. 2019. 22:202-210. doi:10.1089/jmf.2018.0080. | Study design; Comparator
572 | Lin, CT, Gao, Z, Lee, JY. Associations between self-reported weight management methods with diet quality as measured by the Healthy Eating Index-2005. Prev Med. 2013. 57:238-43. doi:10.1016/j.ypmed.2013.05.026. | Study design
573 | Lin, PY, Lin, FY, Chen, TC, Chen, WL, Doong, JY, Shikanai, S, Sarukura, N, Yamamoto, S. Relationship between Sugar Intake and Obesity among School-Age Children in Kaohsiung, Taiwan. J Nutr Sci Vitaminol (Tokyo). 2016. 62:310-316. doi:10.3177/jnsv.62.310. | Study design
574 | Lin, S, Hu, X, Zhang, F, Ruan, Q, Tang, W, Tao, L, Pan, H, Zhang, Q. Effects of egg and milk supplementation on growth and development among children in poor rural area. Zhonghua yu fang yi xue za zhi [chinese journal of preventive medicine]. 2015. 49:733-737. | Language
575 | Lin, WT, Chan, TF, Huang, HL, Lee, CY, Tsai, S, Wu, PW, Yang, YC, Wang, TN, Lee, CH. Fructose-Rich Beverage Intake and Central Adiposity, Uric Acid, and Pediatric Insulin Resistance. J Pediatr. 2016. 171:90-6.e1. doi:10.1016/j.jpeds.2015.12.061. | Study design
576 | Lin, WT, Huang, HL, Huang, MC, Chan, TF, Ciou, SY, Lee, CY, Chiu, YW, Duh, TH, Lin, PL, Wang, TN, Liu, TY, Lee, CH. Effects on uric acid, body mass index and blood pressure in adolescents of consuming beverages sweetened with high-fructose corn syrup. Int J Obes (Lond). 2013. 37:532-9. doi:10.1038/ijo.2012.121. | Study design
577 | Lin, YH, Chang, HT, Tseng, YH, Lin, MH, Chen, YC, Yang, HW, Chen, TJ, Hwang, SJ. Characteristics and health behavior of newly developed metabolic syndrome among community-dwelling elderly in Taiwan. International Journal of Gerontology. 2013. 7:90-96. doi:10.1016/j.ijge.2012.07.003. | Outcome
578 | Liu, S, Song, Y, Ford, ES, Manson, JE, Buring, JE, Ridker, PM. Dietary calcium, vitamin D, and the prevalence of metabolic syndrome in middle-aged and older U.S. women. Diabetes Care. 2005. 28:2926-32. doi:10.2337/diacare.28.12.2926. | Study design
579 | Liu, W. Experimental research into the influence of soy peptide on the volleyball players’ biochemical indexes. Journal of Chemical and Pharmaceutical Research. 2013. 5:364-367. | Intervention/exposure
580 | Liu, X, Xu, W, Cai, H, Gao, YT, Li, H, Ji, BT, Shu, X, Wang, T, Gerszten, RE, Zheng, W, Xiang, YB, Shu, XO. Green tea consumption and risk of type 2 diabetes in Chinese adults: the Shanghai Women’s Health Study and the Shanghai Men’s Health Study. Int J Epidemiol. 2018. 47:1887-1896. doi:10.1093/ije/dyy173. | Outcome
581 | Liu, Z, Qiu, L, Chen, YM, Su, YX. Effect of milk and calcium supplementation on bone density and bone turnover in pregnant Chinese women: a randomized controlled trail. Arch Gynecol Obstet. 2011. 283:205-11. doi:10.1007/s00404-009-1345-0. | Country
582 | Liu, ZM, Ho, SC, Chen, YM, Ho, YP. A mild favorable effect of soy protein with isoflavones on body composition--a 6-month double-blind randomized placebo-controlled trial among Chinese postmenopausal women. Int J Obes (Lond). 2010. 34:309-18. doi:10.1038/ijo.2009.236. | Country; Duplicate
583 | Liu, ZM, Ho, SC, Chen, YM, Ho, YP. A mild favorable effect of soy protein with isoflavones on body compositiona 6-month double-blind randomized placebo-controlled trial among Chinese postmenopausal women. International Journal of Obesity. 2010. 34:309-318. doi:10.1038/ijo.2009.236. | Comparator
584 | Liu, ZM, Ho, SC, Chen, YM, Woo, J. A six-month randomized controlled trial of whole soy and isoflavones daidzein on body composition in equol-producing postmenopausal women with prehypertension. J Obes. 2013. 2013:359763. doi:10.1155/2013/359763. | Intervention/exposure
585 | Lockwood, CM, Moon, JR, Smith, AE, Tobkin, SE, Kendall, KL, Graef, JL, Cramer, JT, Stout, JR. Low-calorie energy drink improves physiological response to exercise in previously sedentary men: a placebo-controlled efficacy and safety study. J Strength Cond Res. 2010. 24:2227-38. doi:10.1519/JSC.0b013e3181aeb0cf. | Comparator
586 | Lockwood, CM, Roberts, MD, Dalbo, VJ, Smith-Ryan, AE, Kendall, KL, Moon, JR, Stout, JR. Effects of Hydrolyzed Whey versus Other Whey Protein Supplements on the Physiological Response to 8 Weeks of Resistance Exercise in College-Aged Males. Journal of the american college of nutrition. 2016. 1-12. doi:10.1080/07315724.2016.1140094. | Intervention/exposure; Comparator
587 | Loh, DA, Moy, FM, Zaharan, NL, Jalaludin, MY, Mohamed, Z. Sugar-sweetened beverage intake and its associations with cardiometabolic risks among adolescents. Pediatr Obes. 2017. 12:e1-e5. doi:10.1111/ijpo.12108. | Study design
588 | Lollo, PC, Amaya-Farfan, J, de Carvalho-Silva, LB. Physiological and physical effects of different milk protein supplements in elite soccer players. J Hum Kinet. 2011. 30:49-57. doi:10.2478/v10078-011-0072-3. | Intervention/exposure; Comparator
589 | Looney, SM, Raynor, HA. Examining the effect of three low-intensity pediatric obesity interventions: a pilot randomized controlled trial. Clin Pediatr (Phila). 2014. 53:1367-74. doi:10.1177/0009922814541803. | Intervention/exposure
590 | Lopez-Barron, RG, Jimenez-Cruz, A, Bacardi-Gascon, M. Modifiable environmental obesity risk factors among elementary school children in a Mexico-us border city. Nutr Hosp. 2015. 31:2047-53. doi:10.3305/nh.2015.31.5.8669. | Study design
591 | Lopez-Garcia, E, van Dam, RM, Rajpathak, S, Willett, WC, Manson, JE, Hu, FB. Changes in caffeine intake and long-term weight change in men and women. Am J Clin Nutr. 2006. 83:674-80. doi:10.1093/ajcn.83.3.674. | Intervention/exposure
592 | Lopez-Garcia, E, van Dam, RM, Willett, WC, Rimm, EB, Manson, JE, Stampfer, MJ, Rexrode, KM, Hu, FB. Coffee consumption and coronary heart disease in men and women: a prospective cohort study. Circulation. 2006. 113:2045-53. doi:10.1161/circulationaha.105.598664. | Outcome
593 | López-Gómez, JJ, Izaola-Jáuregui, O, Torres-Torres, B, Gómez-Hoyos, E, Castro Lozano, Á M, Ortolá-Buigues, A, Martín Ferrero, Á M, De Luis-Román, DA. Influencia de una dieta modificada en la calidad de vida en mujeres con obesidad y artrosis de rodilla antes de la cirugía ortopédica. Nutricion hospitalaria. 2018. 35:71-77. doi:10.20960/nh.1148. | Health status
594 | Lopez-Plaza, B, Bermejo, LM, Koester Weber, T, Parra, P, Serra, F, Hernandez, M, Palma Milla, S, Gomez-Candela, C. Effects of milk supplementation with conjugated linoleic acid on weight control and body composition in healthy overweight people. Nutr Hosp. 2013. 28:2090-8. doi:10.3305/nutr hosp.v28in06.7013. | Comparator
595 | Lopez-Sanchez, GF, Radziminski, L, Skalska, M, Jastrzebska, J, Smith, L, Wakuluk, D, Jastrzebski, Z. Body Composition, Physical Fitness, Physical Activity and Nutrition in Polish and Spanish Male Students of Sports Sciences: Differences and Correlations. Int J Environ Res Public Health. 2019. 16. doi:10.3390/ijerph16071148. | Study design
596 | Lora, KR, Hubbs-Tait, L, Ferris, AM, Wakefield, D. African-American and Hispanic children’s beverage intake: Differences in associations with desire to drink, fathers’ feeding practices, and weight concerns. Appetite. 2016. 107:558-567. doi:10.1016/j.appet.2016.09.012. | Study design
597 | Lotfi, M, Azizi, M, Tahmasbi, W, Bashiri, P. The effects of consuming 6 weeks of beetroot juice (Beta vulgaris l.) on hematological parameters in female soccer players. Journal of Kermanshah University of Medical Sciences. 2018. 22. doi:10.5812/jkums.82300. | Comparator; Outcome
598 | Lovell, AL, Milne, T, Jiang, Y, Chen, RX, Grant, CC, Wall, CR. Evaluation of the effect of a growing up milk lite vs. Cow’s milk on diet quality and dietary intakes in early childhood: The growing up milk lite (GUMLi) randomised controlled trial. Nutrients. 2019. 11. doi:10.3390/nu11010203. | Population at Intervention/exposure
599 | Lowe, MR, Butryn, M, Thomas, G, Coletta, M. A randomized, controlled trial of the effect of meal replacement and energy density interventions on weight loss maintenance. Obesity (silver spring, md.). 2011. 19:S95-. doi:10.1038/oby.2011.226. | Health status; Publication status
600 | Lowe, MR, Butryn, ML, Thomas, JG, Coletta, M. Meal replacements, reduced energy density eating, and weight loss maintenance in primary care patients: a randomized controlled trial. Obesity (Silver Spring). 2014. 22:94-100. doi:10.1002/oby.20582. | Intervention/exposure; Health status
601 | Lowe, MR, Butryn, ML, Zhang, F. Evaluation of meal replacements and a home food environment intervention for long-term weight loss: a randomized controlled trial. Am J Clin Nutr. 2018. 107:12-19. doi:10.1093/ajcn/nqx005. | Intervention/exposure
602 | Lowen, T. Sweet debate: do artificial sweeteners contribute to rather than combat obesity?. Minn Med. 2011. 94:20-3. | Study design
603 | Lowndes, J, Papadopoulos, TF, Lowther, BE, Kawiecki, D, Yu, Z, Pardo, S, Rippe, JM. High-fructose corn syrup and sucrose are nutritionally equivalent and may help improve dietary quality during weight loss. Obesity.. 2011. 19:S115-S116. doi:10.1038/oby.2011.226. | Publication status
604 | Lowndes, J, Sinnett, S, Pardo, S, Nguyen, VT, Melanson, KJ, Yu, Z, Lowther, BE, Rippe, JM. The effect of normally consumed amounts of sucrose or high fructose corn syrup on lipid profiles, body composition and related parameters in overweight/obese subjects. Nutrients. 2014. 6:1128-44. doi:10.3390/nu6031128. | Comparator
605 | Lowndes, J, Sinnett, S, Yu, Z, Rippe, J. The effects of fructose-containing sugars on weight, body composition and cardiometabolic risk factors when consumed at up to the 90th percentile population consumption level for fructose. Nutrients. 2014. 6:3153-68. doi:10.3390/nu6083153. | Comparator
606 | Lu, TM, Chiu, HF, Shen, YC, Chung, CC, Venkatakrishnan, K, Wang, CK. Hypocholesterolemic Efficacy of Quercetin Rich Onion Juice in Healthy Mild Hypercholesterolemic Adults: A Pilot Study. Plant Foods Hum Nutr. 2015. 70:395-400. doi:10.1007/s11130-015-0507-4. | Comparator
607 | Lubans, DR, Morgan, PJ, Aguiar, EJ, Callister, R. Randomized controlled trial of the Physical Activity Leaders (PALs) program for adolescent boys from disadvantaged secondary schools. Prev Med. 2011. 52:239-46. doi:10.1016/j.ypmed.2011.01.009. | Intervention/exposure
608 | Lueangpiansamut, J, Chatrchaiwiwatana, S, Muktabhant, B, Inthalohit, W. Relationship between dental caries status, nutritional status, snack foods, and sugar-sweetened beverages consumption among primary schoolchildren grade 4-6 in Nongbua Khamsaen school, Na Klang district, Nongbua Lampoo Province, Thailand. J Med Assoc Thai. 2012. 95:1090-7. | Study design
609 | Lukaszuk, JM, Luebbers, P, Gordon, BA. Preliminary study: soy milk as effective as skim milk in promoting weight loss. J Am Diet Assoc. 2007. 107:1811-4. doi:10.1016/j.jada.2007.07.008. | Comparator
610 | Lukic, M, Licaj, I, Lund, E, Skeie, G, Weiderpass, E, Braaten, T. Coffee consumption and the risk of cancer in the Norwegian Women and Cancer (NOWAC) Study. European Journal of Epidemiology. 2016. 31:905-916. doi:10.1007/s10654-016-0142-x. | Outcome
611 | Lupton, BS, Fonnebo, V, Sogaard, AJ, Langfeldt, E. The Finnmark Intervention Study. Better health for the fishery population in an Arctic village in North Norway. Scand J Prim Health Care. 2002. 20:213-8. doi:10.1080/028134302321004863. | Intervention/exposure
612 | Lupton, BS, Fonnebo, V, Sogaard, AJ. The Finnmark Intervention Study: is it possible to change CVD risk factors by community-based intervention in an Arctic village in crisis?. Scand J Public Health. 2003. 31:178-86. doi:10.1080/14034940210134077. | Intervention/exposure
613 | Lutsey, PL, Steffen, LM, Stevens, J. Dietary intake and the development of the metabolic syndrome: The atherosclerosis risk in communities study. Circulation. 2008. 117:754-761. doi:10.1161/CIRCULATIONAHA.107.716159. | Outcome
614 | Ma, J, Jacques, PF, Meigs, JB, Fox, CS, Rogers, GT, Smith, CE, Hruby, A, Saltzman, E, McKeown, NM. Sugar-Sweetened Beverage but Not Diet Soda Consumption Is Positively Associated with Progression of Insulin Resistance and Prediabetes. J Nutr. 2016. 146:2544-2550. doi:10.3945/jn.116.234047. | Outcome
615 | Ma, J, Sloan, M, Fox, CS, Hoffmann, U, Smith, CE, Saltzman, E, Rogers, GT, Jacques, PF, McKeown, NM. Sugar-sweetened beverage consumption is associated with abdominal fat partitioning in healthy adults. J Nutr. 2014. 144:1283-90. doi:10.3945/jn.113.188599. | Study design
616 | Ma, L, Grann, K, Li, M, Jiang, Z. A pilot study to evaluate the effect of soy isolate protein on the serum lipid profile and other potential cardiovascular risk markers in moderately hypercholesterolemic Chinese adults. Ecol Food Nutr. 2011. 50:473-85. doi:10.1080/03670244.2011.620875. | Country
617 | Ma, XM, Huang, ZW, Yang, XG, Su, YX. Calcium supplementation and bone mineral accretion in Chinese adolescents aged 12-14 years: a 12-month, dose-response, randomised intervention trial. British journal of nutrition. 2014. 112:1510-1520. doi:10.1017/S0007114514002384. | Outcome
618 | Machado-Fragua, MD, Struijk, EA, Graciani, A, Guallar-Castillon, P, Rodriguez-Artalejo, F, Lopez-Garcia, E. Coffee consumption and risk of physical function impairment, frailty and disability in older adults. Eur J Nutr. 2019. 58:1415-1427. doi:10.1007/s00394-018-1664-7. | Outcome
619 | Machado-Fragua, MD, Struijk, EA, Graciani, A, Guallar-Castillon, P, Rodríguez-Artalejo, F, Lopez-Garcia, E. Coffee consumption and risk of physical function impairment, frailty and disability in older adults. European Journal of Nutrition. 2018. 1-13. doi:10.1007/s00394-018-1664-7. | Outcome
620 | Machado-Rodrigues, AM, Fernandes, RA, Silva, MR, Gama, A, Mourao, I, Nogueira, H, Rosado-Marques, V, Padez, C. Overweight Risk and Food Habits in Portuguese Pre-school Children. J Epidemiol Glob Health. 2018. 8:106-109. doi:10.2991/j.jegh.2017.10.006. | Study design
621 | Machado-Rodrigues, AM, Fernandes, RA, Silva, MR, Gama, A, Mourão, I, Nogueira, H, Rosado-Marques, V, Padez, C. Overweight risk and food habits in Portuguese pre-school children. Journal of Epidemiology and Global Health. 2017. . doi:10.1016/j.jegh.2017.10.006. | Study design
622 | Macintyre, AK, Marryat, L, Chambers, S. Exposure to liquid sweetness in early childhood: artificially-sweetened and sugar-sweetened beverage consumption at 4–5 years and risk of overweight and obesity at 7–8 years. Pediatric Obesity. 2018. 13:755-765. doi:10.1111/ijpo.12284. | Duplicate
623 | Maekawa, T, Nakamura, J, Kitagawa, Y, Shibata, H, Teramoto, T, Tsuchida, T. Effect of long-term intake of “KURO-oolong tea OTPP” on body fat mass and metabolic syndrome risk in over weight volunteers. Japanese pharmacology and therapeutics. 2011. 39:889-900. | Language
624 | Mah, E, Sapper, TN, Chitchumroonchokchai, C, Failla, ML, Schill, KE, Clinton, SK, Bobe, G, Traber, MG, Bruno, RS. alpha-Tocopherol bioavailability is lower in adults with metabolic syndrome regardless of dairy fat co-ingestion: a randomized, double-blind, crossover trial. American journal of clinical nutrition. 2015. 102:1070-1080. doi:10.3945/ajcn.115.118570. | Outcome
625 | Mahdavi, R, Nikniaz, L, Arefhosseini, S. Energy, fluids intake and beverages consumption pattern among lactating women in Tabriz, Iran. Pakistan Journal of Nutrition. 2009. 8:69-73. doi:10.3923/pjn.2009.69.73. | Study design
626 | Mai, XM, Becker, AB, Sellers, EA, Liem, JJ, Kozyrskyj, AL. Infrequent milk consumption plus being overweight may have great risk for asthma in girls. Allergy. 2007. 62:1295-301. doi:10.1111/j.1398-9995.2007.01491.x. | Outcome
627 | Makarem, N, Bandera, EV, Lin, Y, Jacques, PF, Hayes, RB, Parekh, N. Consumption of Sugars, Sugary Foods, and Sugary Beverages in Relation to Adiposity-Related Cancer Risk in the Framingham Offspring Cohort (1991-2013). Cancer Prev Res (Phila). 2018. 11:347-358. doi:10.1158/1940-6207.Capr-17-0218. | Outcome
628 | Makarem, N, Bandera, EV, Lin, Y, Jacques, PF, Hayes, RB, Parekh, N. Consumption of sugars, sugary foods, and sugary beverages in relation to adiposity-related cancer risk in the framingham offspring cohort (1991–2013). Cancer Prevention Research. 2018. 11:347-358. doi:10.1158/1940-6207.CAPR-17-0218. | Outcome
629 | Maki, KC, Nieman, KM, Schild, AL, Kaden, VN, Lawless, AL, Kelley, KM, Rains, TM. Sugar-sweetened product consumption alters glucose homeostasis compared with dairy product consumption in men and women at risk of type 2 diabetes mellitus. J Nutr. 2015. 145:459-66. doi:10.3945/jn.114.204503. | Intervention/exposure
630 | Maki, KC, Reeves, MS, Farmer, M, Yasunaga, K, Matsuo, N, Katsuragi, Y, Komikado, M, Tokimitsu, I, Wilder, D, Jones, F, Blumberg, JB, Cartwright, Y. Green tea catechin consumption enhances exercise-induced abdominal fat loss in overweight and obese adults. J Nutr. 2009. 139:264-70. doi:10.3945/jn.108.098293. | Comparator
631 | Maltais, ML, Ladouceur, JP, Dionne, IJ. The Effect of Resistance Training and Different Sources of Postexercise Protein Supplementation on Muscle Mass and Physical Capacity in Sarcopenic Elderly Men. J Strength Cond Res. 2016. 30:1680-7. doi:10.1519/jsc.0000000000001255. | Comparator
632 | Maltais, ML, Perreault, K, Courchesne-Loyer, A, Lagace, JC, Barsalani, R, Dionne, IJ. Effect of Resistance Training and Various Sources of Protein Supplementation on Body Fat Mass and Metabolic Profile in Sarcopenic Overweight Older Adult Men: A Pilot Study. Int J Sport Nutr Exerc Metab. 2016. 26:71-7. doi:10.1123/ijsnem.2015-0160. | Comparator
633 | Mandal, B, Powell, LM. Child care choices, food intake, and children’s obesity status in the United States. Econ Hum Biol. 2014. 14:50-61. doi:10.1016/j.ehb.2014.04.001. | Study design
634 | Mangala Gowri, P, Mary Minolin, T, Thenmozhi, P, Meena, P, Vimala, S. Effectiveness of cinnamon tea in reducing weight among late obese adolescence. Asian Journal of Pharmaceutical and Clinical Research. 2017. 10:156-159. doi:10.22159/ajpcr.2017.v10i4.16420. | Country
635 | Mantaring, J, Benyacoub, J, Destura, R, Pecquet, S, Vidal, K, Volger, S, Guinto, V. Effect of maternal supplement beverage with and without probiotics during pregnancy and lactation on maternal and infant health: a randomized controlled trial in the Philippines. BMC Pregnancy Childbirth. 2018. 18:193. doi:10.1186/s12884-018-1828-8. | Country
636 | Marangoni, F, Brignoli, O, Cricelli, C, Poli, A. Lifestyle and specific dietary habits in the Italian population: focus on sugar intake and association with anthropometric parameters—the LIZ (Liquidi e Zuccheri nella popolazione Italiana) study. European Journal of Nutrition. 2017. 56:1685-1691. doi:10.1007/s00394-016-1215-z. | Study design
637 | Marcus, C, Nyberg, G, Nordenfelt, A, Karpmyr, M, Kowalski, J, Ekelund, U. A 4-year, cluster-randomized, controlled childhood obesity prevention study: STOPP. Int J Obes (Lond). 2009. 33:408-17. doi:10.1038/ijo.2009.38. | Intervention/exposure
638 | Mariner, WK, Annas, GJ. Limiting “sugary drinks” to reduce obesity--who decides?. N Engl J Med. 2013. 368:1763-5. doi:10.1056/NEJMp1303706. | Study design
639 | Marisela Vazquez Duran, M, Castillo Martinez, L, Orea Tejada, A, Tellez Olvera, DA, Delgado Perez, LG, Marquez Zepeda, B, Pineda Juarez, JA, Lopez Rodriguez, Y. Effect of decreasing the consumption of sweetened caloric and non-caloric beverages on weight, body composition and blood pressure in young adults. European journal of preventive cardiology.. 2013. 20:S120. doi:10.1177/2047487314530052. | Publication status
640 | Marks, GC, Hughes, MC, van der Pols, JC. Relative validity of food intake estimates using a food frequency questionnaire is associated with sex, age, and other personal characteristics. J Nutr. 2006. 136:459-65. doi:10.1093/jn/136.2.459. | Study design; Outcome
641 | Marsh, S, Jiang, Y, Carter, K, Wall, C. Evaluation of a Free Milk in Schools Program in New Zealand: Effects on Children’s Milk Consumption and Anthropometrics. J Sch Health. 2018. 88:596-604. doi:10.1111/josh.12649. | Intervention/exposure
642 | Marshall, TA, Curtis, AM, Cavanaugh, JE, VanBuren, JM, Warren, JJ, Levy, SM. Description of Child and Adolescent Beverage and Anthropometric Measures According to Adolescent Beverage Patterns. Nutrients. 2018. 10. doi:10.3390/nu10080958. | Intervention/exposure
643 | Marshall, TA, Van Buren, JM, Warren, JJ, Cavanaugh, JE, Levy, SM. Beverage Consumption Patterns at Age 13 to 17 Years Are Associated with Weight, Height, and Body Mass Index at Age 17 Years. J Acad Nutr Diet. 2017. 117:698-706. doi:10.1016/j.jand.2017.01.010. | Intervention/exposure
644 | Martín, ISM, Vilar, EG, Barrado, MR, Barato, VP. Soft drink consumption: Do we know what we drink and its implication on health. Mediterranean Journal of Nutrition and Metabolism. 2018. 11:1-10. doi:10.3233/MNM-17158. | Study design
645 | Martin, KR, Bopp, J, Burrell, L, Hook, G. The effect of 100% tart cherry juice on serum uric acid levels, biomarkers of inflammation and cardiovascular disease risk factors. FASEB journal. 2011. 25. | Publication status
646 | Martin, KR, Burrell, L, Bopp, J. Authentic tart cherry juice reduces markers of inflammation in overweight and obese subjects: a randomized, crossover pilot study. Food Funct. 2018. 9:5290-5300. doi:10.1039/c8fo01492b. | Comparator
647 | Martin, KR, Coles, KM. Consumption of 100% Tart Cherry Juice Reduces Serum Urate in Overweight and Obese Adults. Curr Dev Nutr. 2019. 3:nzz011. doi:10.1093/cdn/nzz011. | Comparator
648 | Martins, AP, Benicio, MH. Influence of dietary intake during gestation on postpartum weight retention. Rev Saude Publica. 2011. 45:870-7. doi:10.1590/s0034-89102011005000056. | Publication date
649 | Martins, MLB, Kac, G, Silva, RA, Bettiol, H, Barbieri, MA, Cardoso, VC, Silva, AAM. Dairy consumption is associated with a lower prevalence of metabolic syndrome among young adults from Ribeirão Preto, Brazil. Nutrition. 2015. 31:716-721. doi:10.1016/j.nut.2014.12.017. | Study design
650 | Marventano, S, Ferranti, R, Antoci, M, Giogianni, G, Nolfo, F, Rametta, S, Mistretta, A. Association between sugar-sweetened beverages consumption and body composition in relation to salt among adolescent resident in Sicily, Southern Italy. Current Nutrition and Food Science. 2017. 13:21-28. doi:10.2174/1573401312666161018130011. | Study design
651 | Maskarinec, G, Aylward, AG, Erber, E, Takata, Y, Kolonel, LN. Soy intake is related to a lower body mass index in adult women. European Journal of Nutrition. 2008. 47:138-144. doi:10.1007/s00394-008-0707-x. | Intervention/exposure
652 | Masse, LC, de Niet-Fitzgerald, JE, Watts, AW, Naylor, PJ, Saewyc, EM. Associations between the school food environment, student consumption and body mass index of Canadian adolescents. Int J Behav Nutr Phys Act. 2014. 11:29. doi:10.1186/1479-5868-11-29. | Study design
653 | Mateo, KF, Jay, M. Access to a behavioral weight loss website with or without group sessions increased weight loss in statewide campaign. Journal of Clinical Outcomes Management. 2014. 21:345-348. | Study design
654 | Mathison, B, Kimble, L, McKay, D, Chen, Yo C, Blumberg, J, Kaspar, K, Khoo, C, Chew, B. Chronic consumption of a high polyphenol content cranberry beverage improved glucoregulation and HDL cholesterol in healthy but overweight humans. FASEB journal. 2014. 28. | Publication status
655 | Matsui, Y, Kinoshita, K, Osaki, N, Wakisaka, T, Hibi, M, Katsuragi, Y, Yamaguchi, TF, Fukuhara, I. Effects of tea catechin-rich beverage on abdominal fat area and body weight in obese Japanese individuals-A randomized, double-blind, placebo-controlled, parallel-group study. Japanese Pharmacology and Therapeutics. 2018. 46:1383-1395. | Comparator
656 | Matsui, Y, Takeshita, M, Hibi, M, Osaki, N, Fukuhara, I. Efficacy and safety of powdered beverage containing green tea catechins on body fat in obese adults: a randomized, placebo controlled, double-blind parallel study. Japanese pharmacology and therapeutics. 2016. 44:1013-1023. | Language
657 | Matsuo, T, Matsuo, M, Kasai, M, Takeuchi, H. A liquid diet supplement containing structured medium- and long-chain triacylglycerols dose not increase body fat accumulation in healthy young women. Technical bulletin of the faculty of agriculture, kagawa university. 2001. 53:35. | Intervention/exposure
658 | Matsuo, T, Matsuo, M, Kasai, M, Takeuchi, H. Effects of a liquid diet supplement containing structured medium- and long-chain triacylglycerols on bodyfat accumulation in healthy young subjects. Asia Pac J Clin Nutr. 2001. 10:46-50. | Comparator
659 | Matsuura, H, Mure, K, Nishio, N, Kitano, N, Nagai, N, Takeshita, T. Relationship between coffee consumption and prevalence of metabolic syndrome among Japanese civil servants. J Epidemiol. 2012. 22:160-6. doi:10.2188/jea.je20110068. | Study design
660 | Matsuyama, T, Tanaka, Y, Kamimaki, I, Nagao, T, Tokimitsu, I. Catechin safely improved higher levels of fatness, blood pressure, and cholesterol in children. Obesity (Silver Spring). 2008. 16:1338-48. doi:10.1038/oby.2008.60. | Comparator
661 | Mattei, J, Malik, V, Hu, FB, Campos, H. Substituting homemade fruit juice for sugar-sweetened beverages is associated with lower odds of metabolic syndrome among Hispanic adults. J Nutr. 2012. 142:1081-7. doi:10.3945/jn.111.149344. | Study design
662 | Matthews, VL, Knutsen, SF, Beeson, WL, Fraser, GE. Soy milk and dairy consumption is independently associated with ultrasound attenuation of the heel bone among postmenopausal women: the Adventist Health Study-2. Nutr Res. 2011. 31:766-75. doi:10.1016/j.nutres.2011.09.016. | Outcome
663 | McAdam, JS, McGinnis, KD, Beck, DT, Haun, CT, Romero, MA, Mumford, PW, Roberson, PA, Young, KC, Lohse, KR, Lockwood, CM, Roberts, MD, Sefton, JM. Effect of Whey Protein Supplementation on Physical Performance and Body Composition in Army Initial Entry Training Soldiers. Nutrients. 2018. 10. doi:10.3390/nu10091248. | Comparator
664 | McCaffrey, TA, Rennie, KL, Kerr, MA, Wallace, JM, Hannon-Fletcher, MP, Coward, WA, Jebb, SA, Livingstone, MB. Energy density of the diet and change in body fatness from childhood to adolescence; is there a relation?. Am J Clin Nutr. 2008. 87:1230-7. doi:10.1093/ajcn/87.5.1230. | Intervention/exposure
665 | McGrath, R, Dullea, K, Cunningham, K, Griffin, H, Finucane, FM. Effect of 8 weeks of a milk-based intensive weight management programme on anthropometric and metabolic characteristics of severely obese adults. Irish journal of medical science. 2014. 183:S460-. doi:10.1007/s11845-014-1186-0. | Publication status
666 | McGrath, R, Dullea, K, Cunningham, K, Griffin, H. Effect of eight weeks of a milk-based intensive weight management programme on anthropometric and metabolic characteristics of severely obese adults. Obesity facts. 2014. 7:92-. doi:10.1159/000363668. | Publication status; Duplicate
667 | McMorrow, AM, Weinheimer, EM, Conley, TB, Kobza, VM, Sands, LP, Lim, E, Janle, EM, Campbell, WW. The effects of whey protein supplementation and exercise on bone in overweight/obese middle-aged adults. FASEB journal. 2011. 25. | Publication status
668 | Medeiros, LCS, Speridião, PGL, Sdepanian, VL, Fagundes-Neto, U, Morais, MB. Nutrient intake and nutritional status of children following a diet free from cow’s milk and cow’s milk by-products. Jornal de Pediatria. 2004. 80:363-370. doi:10.2223/1220. | Study design; Population at Intervention/exposure
669 | Mehrabani, S, Salehi-Abargouei, A, Asemi, M, Mehrabani, S, Feizi, A, Safavi, SM. Effect of Low-fat Milk Consumption Compared to Apple Juice and Water on the Energy Intake Among 10-12-Year-Old Obese Boys: A Three-way Cross-over Clinical Trial. Int J Prev Med. 2014. 5:1405-11. | Outcome; Health status
670 | Mejia, W, Cordoba, D, Duran, P, Chacon, Y, Rosselli, D. Effect of Daily Exposure to an Isolated Soy Protein Supplement on Body Composition, Energy and Macronutrient Intake, Bone Formation Markers, and Lipid Profile in Children in Colombia. J Diet Suppl. 2019. 16:1-13. doi:10.1080/19390211.2017.1409851. | Intervention/exposure
671 | Mellendick, K, Shanahan, L, Wideman, L, Calkins, S, Keane, S, Lovelady, C. Diets Rich in Fruits and Vegetables Are Associated with Lower Cardiovascular Disease Risk in Adolescents. Nutrients. 2018. 10. doi:10.3390/nu10020136. | Study design; Intervention/exposure
672 | Metzner, CE, Folberth-Vogele, A, Bitterlich, N, Lemperle, M, Schafer, S, Alteheld, B, Stehle, P, Siener, R. Effect of a conventional energy-restricted modified diet with or without meal replacement on weight loss and cardiometabolic risk profile in overweight women. Nutr Metab (Lond). 2011. 8:64. doi:10.1186/1743-7075-8-64. | Intervention/exposure
673 | Meyer, AM, Evenson, KR, Couper, DJ, Stevens, J, Pereria, MA, Heiss, G. Television, physical activity, diet, and body weight status: the ARIC cohort. Int J Behav Nutr Phys Act. 2008. 5:68. doi:10.1186/1479-5868-5-68. | Intervention/exposure; Outcome
674 | Michaelsen, KF. Cow’s milk in the prevention and treatment of stunting and wasting. Food Nutr Bull. 2013. 34:249-51. doi:10.1177/156482651303400219. | Study design
675 | Michels, KB, Holmberg, L, Bergkvist, L, Wolk, A. Coffee, tea, and caffeine consumption and breast cancer incidence in a cohort of Swedish women. Annals of Epidemiology. 2002. 12:21-26. doi:10.1016/S1047-2797(01)00238-1. | Outcome
676 | Miglani, N, Bains, K, Singh, P. Diet and physical activity in relation to metabolic syndrome among urban Indian men and women. Ecol Food Nutr. 2015. 54:43-56. doi:10.1080/03670244.2014.947403. | Country
677 | Mikulovic, J, Marcellini, A, Compte, R, Duchateau, G, Vanhelst, J, Fardy, PS, Bui-Xuan, G. Prevalence of overweight in adolescents with intellectual deficiency. Differences in socio-educative context, physical activity and dietary habits. Appetite. 2011. 56:403-7. doi:10.1016/j.appet.2010.12.006. | Study design; Intervention/exposure
678 | Miller, GD, Beavers, DP, Hamm, D, Mihalko, SL, Messier, SP. Nutrient Intake During Diet-Induced Weight Loss and Exercise Interventions in a Randomized Trial in Older Overweight and Obese Adults. J Nutr Health Aging. 2017. 21:1216-1224. doi:10.1007/s12603-017-0892-5. | Intervention/exposure
679 | Miller, SA, Taveras, EM, Rifas-Shiman, SL, Gillman, MW. Association between television viewing and poor diet quality in young children. Int J Pediatr Obes. 2008. 3:168-76. doi:10.1080/17477160801915935. | Study design; Intervention/exposure
680 | Miri, SF, Javadi, M, Lin, CY, Griffiths, MD, Björk, M, Pakpour, AH. Effectiveness of cognitive-behavioral therapy on nutrition improvement and weight of overweight and obese adolescents: A randomized controlled trial. Diabetes and Metabolic Syndrome: Clinical Research and Reviews. 2019. 13:2190-2197. doi:10.1016/j.dsx.2019.05.010. | Intervention/exposure
681 | Mirmiran, P, Carlström, M, Bahadoran, Z, Azizi, F. Long-term effects of coffee and caffeine intake on the risk of pre-diabetes and type 2 diabetes: Findings from a population with low coffee consumption. Nutrition, Metabolism and Cardiovascular Diseases. 2018. 28:1261-1266. doi:10.1016/j.numecd.2018.09.001. | Outcome
682 | Mitsou, EK, Kougia, E, Nomikos, T, Yannakoulia, M, Mountzouris, KC, Kyriacou, A. Effect of banana consumption on faecal microbiota: a randomised, controlled trial. Anaerobe. 2011. 17:384-7. doi:10.1016/j.anaerobe.2011.03.018. | Outcome
683 | Mitsui, T, Kasezawa, N, Goda, T. Milk consumption does not affect body mass index but may have an unfavorable effect on serum total cholesterol in Japanese adults. Nutrition Research. 2007. 27:395-399. doi:10.1016/j.nutres.2007.05.006. | Study design
684 | Miyazaki, R, Kotani, K, Ayabe, M, Tsuzaki, K, Shimada, J, Sakane, N, Takase, H, Ichikawa, H, Yonei, Y, Ishii, K. Minor effects of green tea catechin supplementation on cardiovascular risk markers in active older people: a randomized controlled trial. Geriatr Gerontol Int. 2013. 13:622-9. doi:10.1111/j.1447-0594.2012.00952.x. | Comparator
685 | Mobley, CB, Haun, CT, Roberson, PA, Mumford, PW, Romero, MA, Kephart, WC, Anderson, RG, Vann, CG, Osburn, SC, Pledge, CD, Martin, JS, Young, KC, Goodlett, MD, Pascoe, DD, Lockwood, CM, Roberts, MD. Effects of Whey, Soy or Leucine Supplementation with 12 Weeks of Resistance Training on Strength, Body Composition, and Skeletal Muscle and Adipose Tissue Histological Attributes in College-Aged Males. Nutrients. 2017. 9. doi:10.3390/nu9090972. | Intervention/exposure
686 | Mohindra, NA, Nicklas, TA, O’Neil C, E, Yang, SJ, Berenson, GS. Eating patterns and overweight status in young adults: the Bogalusa Heart Study. Int J Food Sci Nutr. 2009. 60 Suppl 3:14-25. doi:10.1080/09637480802322095. | Study design
687 | Mojtahedi, MC, Thorpe, MP, Karampinos, DC, Johnson, CL, Layman, DK, Georgiadis, JG, Evans, EM. The effects of a higher protein intake during energy restriction on changes in body composition and physical function in older women. J Gerontol A Biol Sci Med Sci. 2011. 66:1218-25. doi:10.1093/gerona/glr120. | Intervention/exposure
688 | Molina-Hidalgo, C, De-la, OA, Jurado-Fasoli, L, Amaro-Gahete, FJ, Castillo, MJ. Beer or Ethanol Effects on the Body Composition Response to High-Intensity Interval Training. The BEER-HIIT Study. Nutrients. 2019. 11. doi:10.3390/nu11040909. | Intervention/exposure; Comparator
689 | Moraeus, L, Lissner, L, Olsson, L, Sjoberg, A. Age and time effects on children’s lifestyle and overweight in Sweden. BMC Public Health. 2015. 15:355. doi:10.1186/s12889-015-1635-3. | Study design; Intervention/exposure
690 | Moran, LJ, Noakes, M, Clifton, PM, Wittert, GA, Williams, G, Norman, RJ. Short-term meal replacements followed by dietary macronutrient restriction enhance weight loss in polycystic ovary syndrome. Am J Clin Nutr. 2006. 84:77-87. doi:10.1093/ajcn/84.1.77. | Intervention/exposure
691 | Moreira, NF, da Veiga, GV, Santaliestra-Pasias, AM, Androutsos, O, Cuenca-Garcia, M, de Oliveira, ASD, Pereira, RA, de Moraes, ABV, Van den Bussche, K, Censi, L, Gonzalez-Gross, M, Canada, D, Gottrand, F, Kafatos, A, Marcos, A, Widhalm, K, Molnar, D, Moreno, LA. Clustering of multiple energy balance related behaviors is associated with body fat composition indicators in adolescents: Results from the HELENA and ELANA studies. Appetite. 2018. 120:505-513. doi:10.1016/j.appet.2017.10.008. | Study design
692 | Moreno-Pérez, D, Bressa, C, Bailén, M, Hamed-Bousdar, S, Naclerio, F, Carmona, M, Pérez, M, González-Soltero, R, Montalvo-Lominchar, MG, Carabaña, C, Larrosa, M. Effect of a protein supplement on the gut microbiota of endurance athletes: A randomized, controlled, double-blind pilot study. Nutrients. 2018. 10. doi:10.3390/nu10030337. | Outcome
693 | Morgan, PJ, Collins, CE, Plotnikoff, RC, Cook, AT, Berthon, B, Mitchell, S, Callister, R. Efficacy of a workplace-based weight loss program for overweight male shift workers: the Workplace POWER (Preventing Obesity Without Eating like a Rabbit) randomized controlled trial. Prev Med. 2011. 52:317-25. doi:10.1016/j.ypmed.2011.01.031. | Intervention/exposure
694 | Mori, N, Kano, M, Masuoka, N, Konno, T, Suzuki, Y, Miyazaki, K, Ueki, Y. Effect of probiotic and prebiotic fermented milk on skin and intestinal conditions in healthy young female students. Biosci Microbiota Food Health. 2016. 35:105-12. doi:10.12938/bmfh.2015-022. | Intervention/exposure
695 | Moschonis, G, van den Heuvel, EG, Mavrogianni, C, Singh-Povel, CM, Leotsinidis, M, Manios, Y. Associations of Milk Consumption and Vitamin B(2) and Beta12 Derived from Milk with Fitness, Anthropometric and Biochemical Indices in Children. The Healthy Growth Study. Nutrients. 2016. 8. doi:10.3390/nu8100634. | Study design
696 | Moschonis, G, Van den Heuvel, EGHM, Mavrogianni, C, Singh-Povel, CM, Leotsinidis, M, Manios, Y. Associations of milk consumption and vitamin B2 and b12 derived from milk with fitness, anthropometric and biochemical indices in children. The healthy growth study. Nutrients. 2016. 8. doi:10.3390/nu8100634. | Study design; Duplicate
697 | Mossavar-Rahmani, Y, Kamensky, V, Manson, JE, Silver, B, Rapp, SR, Haring, B, Beresford, SAA, Snetselaar, L, Wassertheil-Smoller, S. Artificially Sweetened Beverages and Stroke, Coronary Heart Disease, and All-Cause Mortality in the Women’s Health Initiative. Stroke. 2019. 50:555-562. doi:10.1161/strokeaha.118.023100. | Outcome
698 | Movassagh E Z, Kontulainen, S, Baxter-Jones, ADG, Whiting, S, Szafron, M, Papadimitropoulos, M, Vatanparast, H. Are milk and alternatives and fruit and vegetable intakes during adolescence associated with cortical and trabecular bone structure, density, and strength in adulthood?. Osteoporosis International. 2017. 28:609-619. doi:10.1007/s00198-016-3775-4. | Intervention/exposure; Outcome
699 | Movassagh, EZ, Baxter-Jones, ADG, Kontulainen, S, Whiting, S, Szafron, M, Vatanparast, H. Vegetarian-style dietary pattern during adolescence has long-term positive impact on bone from adolescence to young adulthood: a longitudinal study. Nutr J. 2018. 17:36. doi:10.1186/s12937-018-0324-3. | Intervention/exposure
700 | Muckelbauer, R, Libuda, L, Clausen, K, Reinehr, T, Kersting, M. A simple dietary intervention in the school setting decreased incidence of overweight in children. Obes Facts. 2009. 2:282-5. doi:10.1159/000229783. | Intervention/exposure; Comparator
701 | Muckelbauer, R, Libuda, L, Clausen, K, Toschke, AM, Reinehr, T, Kersting, M. Immigrational background affects the effectiveness of a school-based overweight prevention program promoting water consumption. Obesity (Silver Spring). 2010. 18:528-34. doi:10.1038/oby.2009.270. | Intervention/exposure; Comparator
702 | Muckelbauer, R, Libuda, L, Clausen, K, Toschke, AM, Reinehr, T, Kersting, M. Promotion and provision of drinking water in schools for overweight prevention: randomized, controlled cluster trial. Pediatrics. 2009. 123:e661-7. doi:10.1542/peds.2008-2186. | Intervention/exposure; Comparator
703 | Mueller, NT, Jacobs, DR, Jr, MacLehose, RF, Demerath, EW, Kelly, SP, Dreyfus, JG, Pereira, MA. Consumption of caffeinated and artificially sweetened soft drinks is associated with risk of early menarche. Am J Clin Nutr. 2015. 102:648-54. doi:10.3945/ajcn.114.100958. | Outcome; Duplicate
704 | Mueller, NT, Jacobs, DR, MacLehose, RF, Demerath, EW, Kelly, SP, Dreyfus, JG, Pereira, MA. Consumption of caffeinated and artificially sweetened soft drinks is associated with risk of early menarche1,2. American Journal of Clinical Nutrition. 2015. 102:648-654. doi:10.3945/ajcn.114.100958. | Outcome
705 | Mueller, NT, Odegaard, AO, Gross, MD, Koh, WP, Yu, MC, Yuan, JM, Pereira, MA. Soy intake and risk of type 2 diabetes mellitus in Chinese Singaporeans: Soy intake and risk of type 2 diabetes. European Journal of Nutrition. 2012. 51:1033-1040. doi:10.1007/s00394-011-0276-2. | Outcome
706 | Mulero, J, Bernabé, J, Cerdá, B, García-Viguera, C, Moreno, DA, Albaladejo, MD, Avilés, F, Parra, S, Abellán, J, Zafrilla, P. Variations on cardiovascular risk factors in metabolic syndrome after consume of a citrus-based juice. Clinical Nutrition. 2012. 31:372-377. doi:10.1016/j.clnu.2011.11.014. | Outcome
707 | Mundt, CA, Baxter-Jones, AD, Whiting, SJ, Bailey, DA, Faulkner, RA, Mirwald, RL. Relationships of activity and sugar drink intake on fat mass development in youths. Med Sci Sports Exerc. 2006. 38:1245-54. doi:10.1249/01.mss.0000227309.18902.fe. | Publication date
708 | Munguía, L, Gutiérrez-Salmeán, G, Hernández, M, Ortiz, A, Sánchez, ME, Nájera, N, Meaney, E, Rubio-Gayosso, I, Ceballos, G. Beneficial effects of a flavanol-enriched cacao beverage on anthropometric and cardiometabolic risk profile in overweight subjects. Revista Mexicana de Cardiologia. 2015. 26:78-86. | Intervention/exposure; Comparator
709 | Myers, G, Prince, RL, Kerr, DA, Devine, A, Woodman, RJ, Lewis, JR, Hodgson, JM. Tea and flavonoid intake predict osteoporotic fracture risk in elderly Australian women: a prospective study. Am J Clin Nutr. 2015. 102:958-65. doi:10.3945/ajcn.115.109892. | Outcome
710 | Mytton, OT, Eyles, H, Ogilvie, D. Evaluating the Health Impacts of Food and Beverage Taxes. Curr Obes Rep. 2014. 3:432-9. doi:10.1007/s13679-014-0123-x. | Intervention/exposure
711 | Nabi, BN, Sedighinejad, A, Haghighi, M, Farzi, F, Rimaz, S, Atrkarroushan, Z, Biazar, G. The anti-obesity effects of green tea: A controlled, randomized, clinical trial. Iranian Red Crescent Medical Journal. 2018. 20. doi:10.5812/ircmj.55950. | Intervention/exposure
712 | Nabuco, HCG, Tomeleri, CM, Fernandes, RR, Sugihara Junior, P, Cavalcante, EF, Cunha, PM, Antunes, M, Nunes, JP, Venturini, D, Barbosa, DS, Burini, RC, Silva, AM, Sardinha, LB, Cyrino, ES. Effect of whey protein supplementation combined with resistance training on body composition, muscular strength, functional capacity, and plasma-metabolism biomarkers in older women with sarcopenic obesity: A randomized, double-blind, placebo-controlled trial. Clinical Nutrition ESPEN. 2019. 32:88-95. doi:10.1016/j.clnesp.2019.04.007. | Intervention/exposure; Health status
713 | Nabuco, HCG, Tomeleri, CM, Fernandes, RR, Sugihara Junior, P, Cavalcante, EF, Venturini, D, Barbosa, DS, Silva, AM, Sardinha, LB, Cyrino, ES. Effects of Protein Intake Beyond Habitual Intakes Associated With Resistance Training on Metabolic Syndrome-Related Parameters, Isokinetic Strength, and Body Composition in Older Women. J Aging Phys Act. 2019. 1-8. doi:10.1123/japa.2018-0370. | Intervention/exposure; Comparator
714 | Nabuco, HCG, Tomeleri, CM, Sugihara Junior, P, Fernandes, RR, Cavalcante, EF, Antunes, M, Ribeiro, AS, Teixeira, DC, Silva, AM, Sardinha, LB, Cyrino, ES. Effects of Whey Protein Supplementation Pre- or Post-Resistance Training on Muscle Mass, Muscular Strength, and Functional Capacity in Pre-Conditioned Older Women: A Randomized Clinical Trial. Nutrients. 2018. 10. doi:10.3390/nu10050563. | Intervention/exposure
715 | Nabuco, HCG, Tomeleri, CM, Sugihara Junior, P, Fernandes, RR, Cavalcante, EF, Venturini, D, Barbosa, DS, Silva, AM, Sardinha, LB, Cyrino, ES. Effects of pre- or post-exercise whey protein supplementation on body fat and metabolic and inflammatory profile in pre-conditioned older women: A randomized, double-blind, placebo-controlled trial. Nutr Metab Cardiovasc Dis. 2019. 29:290-300. doi:10.1016/j.numecd.2018.11.007. | Comparator
716 | Nabuco, HCG, Tomeleri, CM, Sugihara, P, Fernandes, RR, Cavalcante, EF, dos Santos, L, Silva, AM, Sardinha, LB, Cyrino, ES. Effect of whey protein supplementation combined with resistance training on cellular health in pre-conditioned older women: A randomized, double-blind, placebo-controlled trial. Archives of Gerontology and Geriatrics. 2019. 82:232-237. doi:10.1016/j.archger.2019.03.007. | Intervention/exposure; Outcome
717 | Naclerio, F, Larumbe-Zabala, E, Ashrafi, N, Seijo, M, Nielsen, B, Allgrove, J, Earnest, CP. Effects of protein-carbohydrate supplementation on immunity and resistance training outcomes: a double-blind, randomized, controlled clinical trial. Eur J Appl Physiol. 2017. 117:267-277. doi:10.1007/s00421-016-3520-x. | Comparator
718 | Naclerio, F, Larumbe-Zabala, E, Larrosa, M, Centeno, A, Esteve-Lanao, J, Moreno-Perez, D. Intake of Animal Protein Blend Plus Carbohydrate Improves Body Composition With no Impact on Performance in Endurance Athletes. Int J Sport Nutr Exerc Metab. 2019. 1-7. doi:10.1123/ijsnem.2018-0359. | Comparator
719 | Nagao, T, Hase, T, Tokimitsu, I. A green tea extract high in catechins reduces body fat and cardiovascular risks in humans. Obesity (Silver Spring). 2007. 15:1473-83. doi:10.1038/oby.2007.176. | Comparator
720 | Nagao, T, Komine, Y, Soga, S, Meguro, S, Hase, T, Tanaka, Y, Tokimitsu, I. Ingestion of a tea rich in catechins leads to a reduction in body fat and malondialdehyde-modified LDL in men. Am J Clin Nutr. 2005. 81:122-9. doi:10.1093/ajcn/81.1.122. | Comparator
721 | Nagao, T, Ochiai, R, Watanabe, T, Kataoka, K, Komikado, M, Tokimitsu, I, Tsuchida, T. Visceral fat-reducing effect of continuous coffee beverage consumption in obese subjects. Japanese pharmacology and therapeutics. 2009. 37:333-344. | Language
722 | Nakamura, J, Abe, K, Ohta, H, Kiso, Y, Takehara, I, Fukuhara, I, Hirano, T. Lowering effects of the OTPP (Oolong tea polymerized polyphenols) enriched Oolong tea (FOSHU “KURO-Oolong tea OTPP”) on visceral fat in over weight volunteers. Japanese pharmacology and therapeutics. 2008. 36:347-357. | Language
723 | Nakamura, J, Teramoto, T, Abe, K, Ohta, H, Kiso, Y, Takehara, I, Fukuhara, I, Hirano, T. Lowering effects on visceral fat of the OTPP (oolong tea polymerized polyphenols) enriched oolong tea (FOSHU “KURO-oolong tea OTPP”) in over weight volunteers. Japanese pharmacology and therapeutics. 2007. 35:661-671. | Language
724 | Narotzki, B, Reznick, AZ, Navot-Mintzer, D, Dagan, B, Levy, Y. Green tea and vitamin E enhance exercise-induced benefits in body composition, glucose homeostasis, and antioxidant status in elderly men and women. J Am Coll Nutr. 2013. 32:31-40. doi:10.1080/07315724.2013.767661. | Intervention/exposure
725 | Nascimento, VG, da Silva, JP, Ferreira, PC, Bertoli, CJ, Leone, C. Maternal breastfeeding, early introduction of non-breast milk, and excess weight in preschoolers. Rev Paul Pediatr. 2016. 34:454-459. doi:10.1016/j.rpped.2016.05.004. | Study design
726 | Natale, RA, Lopez-Mitnik, G, Uhlhorn, SB, Asfour, L, Messiah, SE. Effect of a child care center-based obesity prevention program on body mass index and nutrition practices among preschool-aged children. Health Promot Pract. 2014. 15:695-705. doi:10.1177/1524839914523429. | Intervention/exposure
727 | Navarro, AM, Martinez-Gonzalez, MA, Gea, A, Ramallal, R, Ruiz-Canela, M, Toledo, E. Coffee consumption and risk of hypertension in the SUN Project. Clinical Nutrition. 2019. 38:389-397. doi:10.1016/j.clnu.2017.12.009. | Outcome
728 | Nelson, JA, Carpenter, K, Chiasson, MA. Diet, activity, and overweight among preschool-age children enrolled in the Special Supplemental Nutrition Program for Women, Infants, and Children (WIC). Prev Chronic Dis. 2006. 3:A49. | Study design
729 | Nezami, BT, Ward, DS, Lytle, LA, Ennett, ST, Tate, DF. A mHealth randomized controlled trial to reduce sugar-sweetened beverage intake in preschool-aged children. Pediatr Obes. 2018. 13:668-676. doi:10.1111/ijpo.12258. | Intervention/exposure
730 | Nickols-Richardson, SM, Piehowski, KE, Metzgar, CJ, Miller, DL, Preston, AG. Changes in body weight, blood pressure and selected metabolic biomarkers with an energy-restricted diet including twice daily sweet snacks and once daily sugar-free beverage. Nutr Res Pract. 2014. 8:695-704. doi:10.4162/nrp.2014.8.6.695. | Intervention/exposure
731 | Nicolucci, AC, Hume, MP, Martinez, I, Mayengbam, S, Walter, J, Reimer, RA. Prebiotics Reduce Body Fat and Alter Intestinal Microbiota in Children Who Are Overweight or With Obesity. Gastroenterology. 2017. 153:711-722. doi:10.1053/j.gastro.2017.05.055. | Comparator
732 | Nirengi, S, Amagasa, S, Homma, T, Yoneshiro, T, Matsumiya, S, Kurosawa, Y, Sakane, N, Ebi, K, Saito, M, Hamaoka, T. Daily ingestion of catechin-rich beverage increases brown adipose tissue density and decreases extramyocellular lipids in healthy young women. Springerplus. 2016. 5:1363. doi:10.1186/s40064-016-3029-0. | Comparator
733 | Nissinen, K, Mikkila, V, Mannisto, S, Lahti-Koski, M, Rasanen, L, Viikari, J, Raitakari, OT. Sweets and sugar-sweetened soft drink intake in childhood in relation to adult BMI and overweight. The Cardiovascular Risk in Young Finns Study. Public Health Nutr. 2009. 12:2018-26. doi:10.1017/s1368980009005849. | Publication date
734 | Niv, E, Shapira, Y, Akiva, I, Rokhkind, E, Naor, E, Arbiv, M, Vaisman, N. Effect of levan supplement in orange juice on weight, gastrointestinal symptoms and metabolic profile of healthy subjects: results of an 8-week clinical trial. Nutrients. 2012. 4:638-47. doi:10.3390/nu4070638. | Comparator
735 | Njike, VY, Faridi, Z, Shuval, K, Dutta, S, Kay, CD, West, SG, Kris-Etherton, PM, Katz, DL. Effects of sugar-sweetened and sugar-free cocoa on endothelial function in overweight adults. Int J Cardiol. 2011. 149:83-8. doi:10.1016/j.ijcard.2009.12.010. | Publication date (SSB published before 2012)
736 | Noakes, M, Foster, PR, Keogh, JB, Clifton, PM. Meal replacements are as effective as structured weight-loss diets for treating obesity in adults with features of metabolic syndrome. J Nutr. 2004. 134:1894-9. doi:10.1093/jn/134.8.1894. | Intervention/exposure
737 | Noh, HY, Song, YJ, Lee, JE, Joung, H, Park, MK, Li, SJ, Paik, HY. Dietary patterns are associated with physical growth among school girls aged 9-11 years. Nutr Res Pract. 2011. 5:569-77. doi:10.4162/nrp.2011.5.6.569. | Intervention/exposure
738 | Nordestgaard, AT, Thomsen, M, Nordestgaard, BG. Coffee intake and risk of obesity, metabolic syndrome and type 2 diabetes: a Mendelian randomization study. Int J Epidemiol. 2015. 44:551-65. doi:10.1093/ije/dyv083. | Study design
739 | Norton, C, Toomey, C, McCormack, WG, Francis, P, Saunders, J, Kerin, E, Jakeman, P. Protein Supplementation at Breakfast and Lunch for 24 Weeks beyond Habitual Intakes Increases Whole-Body Lean Tissue Mass in Healthy Older Adults. J Nutr. 2016. 146:65-9. doi:10.3945/jn.115.219022. | Comparator
740 | Novotny, JA, Baer, DJ, Khoo, C, Gebauer, S. Low calorie cranberry juice reduces risk factors of cardiovascular disease in adults. Circulation. 2012. 126. | Publication status
741 | Novotny, JA, Baer, DJ, Khoo, C, Gebauer, SK, Charron, CS. Cranberry juice consumption lowers markers of cardiometabolic risk, including blood pressure and circulating C-reactive protein, triglyceride, and glucose concentrations in adults. J Nutr. 2015. 145:1185-93. doi:10.3945/jn.114.203190. | Outcome
742 | Novotny, R, Daida, YG, Acharya, S, Grove, JS, Vogt, TM. Dairy intake is associated with lower body fat and soda intake with greater weight in adolescent girls. J Nutr. 2004. 134:1905-9. doi:10.1093/jn/134.8.1905. | Study design
743 | Novotny, R, Wilkens, LR, Nigg, CR, Braun, K, Butel, J, Areta, A, Coleman, P, Belyeu-Camacho, T, Greenberg, J, Bersamin, A, etal, . Effectiveness of the Children’s Healthy Living (CHL) multilevel multicomponent community intervention program in 5 US affiliated pacific jurisdictions. FASEB journal. 2017. 31. | Publication status
744 | Nowak, MA. Physical Activity and its Associations with other Lifestyle Elements in Polish Women. J Hum Kinet. 2011. 29:161-72. doi:10.2478/v10078-011-0050-9. | Study design; Intervention/exposure
745 | Nystrom, CD, Sandin, S, Henriksson, P, Henriksson, H, Trolle-Lagerros, Y, Larsson, C, Maddison, R, Ortega, FB, Pomeroy, J, Ruiz, JR, Silfvernagel, K, Timpka, T, Lof, M. Mobile-based intervention intended to stop obesity in preschool-aged children: the MINISTOP randomized controlled trial. Am J Clin Nutr. 2017. 105:1327-1335. doi:10.3945/ajcn.116.150995. | Intervention/exposure
746 | Oben, JE, Enyegue, DM, Fomekong, GI, Soukontoua, YB, Agbor, GA. The effect of Cissus quadrangularis (CQR-300) and a Cissus formulation (CORE) on obesity and obesity-induced oxidative stress. Lipids in health and disease. 2007. 6:4. doi:10.1186/1476-511X-6-4. | Intervention/exposure
747 | O’Connell, BN, Weinheimer, EM, Martin, BR, Weaver, CM, Campbell, WW. Water turnover assessment in overweight adolescents. Obesity (Silver Spring). 2011. 19:292-7. doi:10.1038/oby.2010.225. | Study design; Comparator
748 | O’Connor, L, Imamura, F, Lentjes, MA, Khaw, KT, Wareham, NJ, Forouhi, NG. Prospective associations and population impact of sweet beverage intake and type 2 diabetes, and effects of substitutions with alternative beverages. Diabetologia. 2015. 58:1474-83. doi:10.1007/s00125-015-3572-1. | Outcome
749 | Ohnaka, K, Ikeda, M, Maki, T, Okada, T, Shimazoe, T, Adachi, M, Nomura, M, Takayanagi, R, Kono, S. Effects of 16-week consumption of caffeinated and decaffeinated instant coffee on glucose metabolism in a randomized controlled trial. J Nutr Metab. 2012. 2012:207426. doi:10.1155/2012/207426. | Intervention/exposure
750 | Ohnaka, K, Kohno, M, Adachi, M, Kawate, H, Nomura, M, Kono, S, Takayanagi, R. A randomized controlled trial of 16-week consumption of caffeinated and decaffeinated instant coffee on glucose metabolism in overweight men. Endocrine reviews. 2013. 34. | Publication status
751 | Okop, KJ, Lambert, EV, Alaba, O, Levitt, NS, Luke, A, Dugas, L, Rvh, D, Kroff, J, Micklesfield, LK, Kolbe-Alexander, TL, Warren, S, Dugmore, H, Bobrow, K, Odunitan-Wayas, FA, Puoane, T. Sugar-sweetened beverage intake and relative weight gain among South African adults living in resource-poor communities: longitudinal data from the STOP-SA study. Int J Obes (Lond). 2019. 43:603-614. doi:10.1038/s41366-018-0216-9. | Country
752 | Olafsdottir, AS, Skuladottir, GV, Thorsdottir, I, Hauksson, A, Steingrimsdottir, L. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond). 2006. 30:492-9. doi:10.1038/sj.ijo.0803184. | Other (e.g., duplicative data)
753 | Olafsdottir, S, Berg, C, Eiben, G, Lanfer, A, Reisch, L, Ahrens, W, Kourides, Y, Molnar, D, Moreno, LA, Siani, A, Veidebaum, T, Lissner, L. Young children’s screen activities, sweet drink consumption and anthropometry: results from a prospective European study. Eur J Clin Nutr. 2014. 68:223-8. doi:10.1038/ejcn.2013.234. | Intervention/exposure
754 | Olaya, G, Buitrago, MF, Fewtrell, M. Randomised trial testing new complementary feeding guidelines: effects on food consumption and growth at 6 years of age. Journal of pediatric gastroenterology and nutrition. 2018. 66:1160-. | Publication status
755 | Oliver, P, Riddell, LJ, Lim, K, Keast, RSJ. The acute effects of caffeine in a sugar-sweetened beverage on energy consumption. Journal of Caffeine Research. 2012. 2:133-139. doi:10.1089/jcr.2012.0023. | Intervention/exposure; Comparator; Outcome
756 | Olsson, J, Sundberg, B, Viberg, A, Haenni, A. Effect of a vegetable-oil emulsion on body composition; a 12-week study in overweight women on a meal replacement therapy after an initial weight loss: a randomized controlled trial. Eur J Nutr. 2011. 50:235-42. doi:10.1007/s00394-010-0131-x. | Comparator
757 | Olthof, M, De Ruyter, J, Kuijper, L, Chow, C, Hall, K, Katan, M. Impact of a sugary beverage on body weight goes up with initial BMI in children. Annals of nutrition and metabolism. Conference: 12th european nutrition conference, FENS 2015. Berlin germany. Conference start: 20151020. Conference end: 20151023. Conference publication: (var.pagings). 2015. 67:187-188. doi:10.1159/000440895. | Publication status
758 | Ooi, EM, Adams, LA, Zhu, K, Lewis, JR, Kerr, DA, Meng, X, Solah, V, Devine, A, Binns, CW, Prince, RL. Consumption of a whey protein-enriched diet may prevent hepatic steatosis associated with weight gain in elderly women. Nutr Metab Cardiovasc Dis. 2015. 25:388-95. doi:10.1016/j.numecd.2014.11.005. | Comparator
759 | Oosterhoff, M, Joore, MA, Bartelink, NHM, Winkens, B, Schayck, OCP, Bosma, H. Longitudinal analysis of health disparities in childhood. Arch Dis Child. 2019. . doi:10.1136/archdischild-2018-316482. | Intervention/exposure
760 | Oropeza, L, Garca, O, Ronquillo, D, Martnez, G, Camacho, M, Caamao, M. Supplementation with milk proteins and micronutrients improves bone mineralization and micronutrient intake but is equally effective than nutrition education to reduce body weight of obese children. FASEB journal. 2014. 28. | Publication status
761 | Orsatti, FL, Maesta, N, de Oliveira, EP, Nahas Neto, J, Burini, RC, Nunes, PRP, Souza, AP, Martins, FM, Nahas, EP. Adding Soy Protein to Milk Enhances the Effect of Resistance Training on Muscle Strength in Postmenopausal Women. J Diet Suppl. 2018. 15:140-152. doi:10.1080/19390211.2017.1330794. | Intervention/exposure
762 | Ota, N, Soga, S, Shimotoyodome, A, Haramizu, S, Inaba, M, Murase, T, Tokimitsu, I. Effects of combination of regular exercise and tea catechins intake on energy expenditure in humans. Journal of Health Science. 2005. 51:233-236. doi:10.1248/jhs.51.233. | Intervention/exposure; Outcome
763 | Ottestad, I, Løvstad, AT, Gjevestad, GO, Hamarsland, H, Šaltytė Benth, J, Andersen, LF, Bye, A, Biong, AS, Retterstøl, K, Iversen, PO, Raastad, T, Ulven, SM, Holven, KB. Intake of a protein-enriched milk and effects on muscle mass and strength. A 12-week randomized placebo controlled trial among community-dwelling older adults. Journal of Nutrition, Health and Aging. 2017. 21:1160-1169. doi:10.1007/s12603-016-0856-1. | Comparator
764 | Packianathan, I, Sheikh, M, Boniface, D, Finer, N. Predictors of programme adherence and weight loss in women in an obesity programme using meal replacements. Diabetes Obes Metab. 2005. 7:439-47. doi:10.1111/j.1463-1326.2004.00451.x. | Health status
765 | Padro, T, Vilahur, G, Sanchez-Hernandez, J, Hernandez, M, Antonijoan, RM, Perez, A, Badimon, L. Lipidomic changes of LDL in overweight and moderately hypercholesterolemic subjects taking phytosterol- and omega-3-supplemented milk. J Lipid Res. 2015. 56:1043-56. doi:10.1194/jlr.P052217. | Comparator
766 | Pal, S, Ellis, V, Dhaliwal, S. Effects of whey protein isolate on body composition, lipids, insulin and glucose in overweight and obese individuals. Br J Nutr. 2010. 104:716-23. doi:10.1017/s0007114510000991. | Comparator
767 | Pal, S, Ellis, V. Chronic effects of whey protein on satiety in overweight and obese individuals. Obesity.. 2011. 19:S114-S115. doi:10.1038/oby.2011.226. | Publication status
768 | Palatini, P, Fania, C, Mos, L, Garavelli, G, Mazzer, A, Cozzio, S, Saladini, F, Casiglia, E. Coffee consumption and risk of cardiovascular events in hypertensive patients. Results from the HARVEST. International Journal of Cardiology. 2016. 212:131-137. doi:10.1016/j.ijcard.2016.03.006. | Outcome
769 | Palmer, JR, Boggs, DA, Krishnan, S, Hu, FB, Singer, M, Rosenberg, L. Sugar-sweetened beverages and incidence of type 2 diabetes mellitus in African American women. Arch Intern Med. 2008. 168:1487-92. doi:10.1001/archinte.168.14.1487. | Publication date
770 | Pan, A, Malik, VS, Schulze, MB, Manson, JE, Willett, WC, Hu, FB. Plain-water intake and risk of type 2 diabetes in young and middle-aged women. Am J Clin Nutr. 2012. 95:1454-60. doi:10.3945/ajcn.111.032698. | Outcome
771 | Pang, J, Zhang, Z, Zheng, T, Yang, YJ, Li, N, Bai, M, Peng, Y, Zhang, J, Li, Q, Zhang, B. Association of green tea consumption with risk of coronary heart disease in Chinese population. International Journal of Cardiology. 2015. 179:275-278. doi:10.1016/j.ijcard.2014.11.093. | Outcome
772 | Pantea-Stoian, A, Chilianu, S, Stefanca, F, Elian, V, Serafinceanu, C. The impact of nutrition, sedentary behaviour and lifestyle on school-age children. Romanian Journal of Diabetes, Nutrition and Metabolic Diseases. 2015. 22:241-249. doi:10.1515/rjdnmd-2015-0030. | Study design
773 | Papandreou, D, Andreou, E, Heraclides, A, Rousso, I. Is beverage intake related to overweight and obesity in school children?. Hippokratia. 2013. 17:42-6. | Study design
774 | Papandreou, D, Malindretos, P, Rousso, I. Risk factors for childhood obesity in a Greek paediatric population. Public Health Nutr. 2010. 13:1535-9. doi:10.1017/s1368980009993156. | Study design
775 | Papier, K, D’Este, C, Bain, C, Banwell, C, Seubsman, S, Sleigh, A, Jordan, S. Consumption of sugar-sweetened beverages and type 2 diabetes incidence in Thai adults: results from an 8-year prospective study. Nutr Diabetes. 2017. 7:e283. doi:10.1038/nutd.2017.27. | Outcome
776 | Park, EH, Oh, MS, Kim, S, Lee, J, Kang, KS. The Analysis of Factors Causing the High Prevalence of Child Obesity in Jeju Island. Pediatr Gastroenterol Hepatol Nutr. 2018. 21:127-133. doi:10.5223/pghn.2018.21.2.127. | Study design
777 | Park, JY, Kim, JY, Lee, SP, Lee, JH. The Effect of Green Coffee Bean Extract Supplementation on Body Fat Reduction in Overweight/Obese Women. Korean journal of nutrition. 2010. 43:374-381. doi:10.4163/kjn.2010.43.4.374. | Language
778 | Park, S. Removing dietary liquid calories prevents accelerated body mass index increase. Journal of pediatrics. 2013. 162:655-. doi:10.1016/j.jpeds.2012.12.090. | Study design; (e.g., duplicative data)
779 | Patel, L, Alicandro, G, La Vecchia, C. Low-calorie beverage consumption, diet quality and cardiometabolic risk factors in British adults. Nutrients. 2018. 10. doi:10.3390/nu10091261. | Study design
780 | Patil, YR. An open lable clinical study to evaluate effect of juice of Tinospora cordifolia Linn. On growth of children. International Journal of Research in Ayurveda and Pharmacy. 2012. 3:77-79. | Country
781 | Payab, M, Kelishadi, R, Qorbani, M, Esmaeil Motlagh, M, Hasani-Ranjbar, S, Ejtahed, HS, Ardalan, G, Arefirad, T, Asayesh, H, Heshmat, R. Association of healthy foods intake with anthropometric measures and blood pressure in a national sample of Iranian children and adolescents: the CASPIAN- IV study. Minerva Pediatr. 2016. . | Study design
782 | Pbert, L, Druker, S, Gapinski, MA, Gellar, L, Magner, R, Reed, G, Schneider, K, Osganian, S. A school nurse-delivered intervention for overweight and obese adolescents. J Sch Health. 2013. 83:182-93. doi:10.1111/josh.12014. | Intervention/exposure
783 | Peake, JM, Kukuljan, S, Nowson, CA, Sanders, K, Daly, RM. Inflammatory cytokine responses to progressive resistance training and supplementation with fortified milk in men aged 50+ years: an 18-month randomized controlled trial. Eur J Appl Physiol. 2011. 111:3079-88. doi:10.1007/s00421-011-1942-z. | Intervention/exposure; Other (e.g., duplicative data)
784 | Petrogianni, M, Grammatikaki, E, Kalogeropoulos, N, Peristeraki, A, Moschonis, G, Pitsavos, C, Antonopoulou, S, Manios, Y. Additional benefit in CVD risk indices derived from the consumption of fortified milk when combined with a lifestyle intervention. Public Health Nutr. 2014. 17:440-9. doi:10.1017/s1368980012005265. | Intervention/exposure; Outcome
785 | Petrogianni, M, Grammatikaki, E, Pitsavos, C, Moschonis, G, Alexopoulos, EC, Manios, Y. Changes in CVD risk factors after combined dietary counselling and supplementation with lipid-lowering milk product: The effect of compliance. e-SPEN Journal. 2012. 7:e205-e210. doi:10.1016/j.clnme.2012.06.002. | Comparator
786 | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, T, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, etal, . Does Partial Meal Replacement During Pregnancy Reduce 12-Month Postpartum Weight Retention?. Obesity (silver spring, md.). 2018. (no pagination). doi:10.1002/oby.22361. | Intervention/exposure; Publication status
787 | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, T, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, Yin, E, Phipps, MG, Keadle, S, Abrams, B. Does Partial Meal Replacement During Pregnancy Reduce 12-Month Postpartum Weight Retention?. Obesity (Silver Spring). 2019. 27:226-236. doi:10.1002/oby.22361. | Intervention/exposure
788 | Phelan, S, Wing, RR, Brannen, A, McHugh, A, Hagobian, TA, Schaffner, A, Jelalian, E, Hart, CN, Scholl, TO, Munoz-Christian, K, Yin, E, Phipps, MG, Keadle, S, Abrams, B. Randomized controlled clinical trial of behavioral lifestyle intervention with partial meal replacement to reduce excessive gestational weight gain. Am J Clin Nutr. 2018. 107:183-194. doi:10.1093/ajcn/nqx043. | Intervention/exposure
789 | Phelan, S, Wing, RR, Loria, CM, Kim, Y, Lewis, CE. Prevalence and predictors of weight-loss maintenance in a biracial cohort: results from the coronary artery risk development in young adults study. Am J Prev Med. 2010. 39:546-54. doi:10.1016/j.amepre.2010.08.008. | Study design
790 | Phillips, SM, Bandini, LG, Naumova, EN, Cyr, H, Colclough, S, Dietz, WH, Must, A. Energy-dense snack food intake in adolescence: longitudinal relationship to weight and fatness. Obes Res. 2004. 12:461-72. doi:10.1038/oby.2004.52. | Publication date
791 | Phillips, SM. Optimizing body composition during weight loss: the role of milk products. Can Nurse. 2012. 108:5. | Study design
792 | Piccolo, BD, Comerford, KB, Karakas, SE, Knotts, TA, Fiehn, O, Adams, SH. Whey protein supplementation does not alter plasma branched-chained amino acid profiles but results in unique metabolomics patterns in obese women enrolled in an 8-week weight loss trial. J Nutr. 2015. 145:691-700. doi:10.3945/jn.114.203943. | Intervention/exposure; Health status
793 | Piernas, C, Tate, DF, Popkin, BM. Does diet beverage intake affect consumption patterns? results from the choice RCT study. Obesity.. 2011. 19:S70. doi:10.1038/oby.2011.222. | Outcome; Publication status
794 | Pilaczyńska-Szczȩśniak, Ł, Rzymski, P, Pischel, I. Influence of combined botanical extract preparation on body composition - Results from double blind randomized clinical trial. Archives of Medical Science. 2006. 2:171-178. | Intervention/exposure
795 | Pilolla, K, Sweat, W, Maddalozzo, G, Manore, M. Impact of dietary protein (PRO) intake and high-intensity interval exercise on abdominal obesity (AbOb) and metabolic syndrome (MetS) risk in premenopausal women. FASEB journal. 2012. 26. | Publication status
796 | Pittler, MH. Camellia sinensis (green tea) catechins seem to affect body composition positively: commentary. Focus on alternative and complementary therapies. 2009. 14:98-99. | Study design
797 | Pobocik, RS, Heathcote, GM, Spiers, JB, Otto, CT. Nutritional and anthropometric assessment of a sample of pregnant women and young children in Palau. Asia Pac J Clin Nutr. 2000. 9:102-14. | Study design
798 | Pokimica, B, Garcia-Conesa, MT, Zec, M, Debeljak-Martacic, J, Rankovic, S, Vidovic, N, Petrovic-Oggiano, G, Konic-Ristic, A, Glibetic, M. Chokeberry Juice Containing Polyphenols Does Not Affect Cholesterol or Blood Pressure but Modifies the Composition of Plasma Phospholipids Fatty Acids in Individuals at Cardiovascular Risk. Nutrients. 2019. 11. doi:10.3390/nu11040850. | Comparator
799 | Poole, CN, Roberts, MD, Dalbo, VJ, Tucker, PS, Sunderland, KL, DeBolt, ND, Billbe, BW, Kerksick, CM. The combined effects of exercise and ingestion of a meal replacement in conjunction with a weight loss supplement on body composition and fitness parameters in college-aged men and women. J Strength Cond Res. 2011. 25:51-60. doi:10.1519/JSC.0b013e3181fee4aa. | Intervention/exposure
800 | Potter, AS, Foroudi, S, Stamatikos, A, Patil, BS, Deyhim, F. Drinking carrot juice increases total antioxidant status and decreases lipid peroxidation in adults. Nutr J. 2011. 10:96. doi:10.1186/1475-2891-10-96. | Study design
801 | [Public title] Effect of ImmunocalÂ® with exercise versus casein with exercise on aging processes in elderly persons; [Official title] Effect of the cysteine-rich whey protein isolate (ImmunocalÂ®) in combination with physical exercise on muscle function, body composition and inflammatory cytokine levels in elderly persons: a randomized, double-blind study. Clinicaltrials.gov [http://clinicaltrials.gov]. 2009. . | Publication status
802 | Qi, Y, Niu, J. DOES CHILDHOOD NUTRITION PREDICT HEALTH OUTCOMES DURING ADULTHOOD? EVIDENCE FROM A POPULATION-BASED STUDY IN CHINA. J Biosoc Sci. 2015. 47:650-66. doi:10.1017/s0021932014000509. | Study design; Country
803 | Quinn Rothacker, D. Five-year self-management of weight using meal replacements: comparison with matched controls in rural Wisconsin. Nutrition. 2000. 16:344-8. | Study design
804 | Raben, A, Moller, BK, Flint, A, Vasilaris, TH, Christina Moller, A, Juul Holst, J, Astrup, A. Increased postprandial glycaemia, insulinemia, and lipidemia after 10 weeks’ sucrose-rich diet compared to an artificially sweetened diet: a randomised controlled trial. Food Nutr Res. 2011. 55. doi:10.3402/fnr.v55i0.5961. | Intervention/exposure
805 | Raben, A, Vasilaras, TH, Moller, AC, Astrup, A. Sucrose compared with artificial sweeteners: different effects on ad libitum food intake and body weight after 10 wk of supplementation in overweight subjects. Am J Clin Nutr. 2002. 76:721-9. doi:10.1093/ajcn/76.4.721. | Intervention/exposure
806 | Raja, B, Kaviarasan, K, Arjunan, MM, Pugalendi, KV. Effect of Melothria maderaspatana leaf-tea consumption on blood pressure, lipid profile, anthropometry, fibrinogen, bilirubin, and albumin levels in patients with hypertension. J Altern Complement Med. 2007. 13:349-54. doi:10.1089/acm.2006.5373. | Comparator; Health status; Country
807 | Ramezani Tehrani, F, Moslehi, N, Asghari, G, Gholami, R, Mirmiran, P, Azizi, F. Intake of dairy products, calcium, magnesium, and phosphorus in childhood and age at menarche in the Tehran Lipid and Glucose Study. PLoS One. 2013. 8:e57696. doi:10.1371/journal.pone.0057696. | Outcome
808 | Rangan, A, Zheng, M, Olsen, NJ, Rohde, JF, Heitmann, BL. Dietary intake, weight gain and sleep patterns in young children predisposed to overweight. Annals of nutrition & metabolism. 2017. 71:538-539. doi:10.1159/000480486. | Publication status
809 | Rangel, O, Rico, M, Vallejo, F, Boza, J, Kellerhals, M, Perez de la Cruz, A, Tomas-Barbera, F, Gil, A, Mesa, M, Aguilera, C. Consumption of a polyphenol-rich orange juice improves endothelial biomarkers in overweight and obese adults(bionaos study). Annals of nutrition and metabolism.. 2013. 63:213. doi:10.1159/000354245. | Publication status
810 | Rangel-Huerta, OD, Aguilera, CM, Martin, MV, Soto, MJ, Rico, MC, Vallejo, F, Tomas-Barberan, F, Perez-de-la-Cruz, AJ, Gil, A, Mesa, MD. Normal or High Polyphenol Concentration in Orange Juice Affects Antioxidant Activity, Blood Pressure, and Body Weight in Obese or Overweight Adults. J Nutr. 2015. 145:1808-16. doi:10.3945/jn.115.213660. | Comparator
811 | Rasica, L, Porcelli, S, Marzorati, M, Salvadego, D, Vezzoli, A, Agosti, F, De Col, A, Tringali, G, Jones, AM, Sartorio, A, Grassi, B. Ergogenic effects of beetroot juice supplementation during severe-intensity exercise in obese adolescents. Am J Physiol Regul Integr Comp Physiol. 2018. 315:R453-r460. doi:10.1152/ajpregu.00017.2018. | Health status
812 | Raynor, HA, Van Walleghen, EL, Bachman, JL, Looney, SM, Phelan, S, Wing, RR. Dietary energy density and successful weight loss maintenance. Eat Behav. 2011. 12:119-25. doi:10.1016/j.eatbeh.2011.01.008. | Study design
813 | Raynor, HA, Van Walleghen, EL, Osterholt, KM, Hart, CN, Jelalian, E, Wing, RR, Goldfield, GS. The relationship between child and parent food hedonics and parent and child food group intake in children with overweight/obesity. J Am Diet Assoc. 2011. 111:425-30. doi:10.1016/j.jada.2010.12.013. | Study design
814 | Rebholz, CM, Young, BA, Katz, R, Tucker, KL, Carithers, TC, Norwood, AF, Correa, A. Patterns of Beverages Consumed and Risk of Incident Kidney Disease. Clin J Am Soc Nephrol. 2019. 14:49-56. doi:10.2215/cjn.06380518. | Outcome
815 | Reducing sugary beverage consumption in childhood may lessen chronic disease risk. Journal of the American Dental Association (1939). 2007. 138:160. doi:10.14219/jada.archive.2007.0128. | Publication status
816 | Reichert, RG, Lyon, MR, Kacinik, V, Gahler, RJ, Manjoo, P, Purnama, M, Wood, S. Decreasing cardiovascular risk factors in obese individuals using a combination of PGX(R) meal replacements and PGX(R) granules in a 12-week clinical weight modification program. J Complement Integr Med. 2013. 10. doi:10.1515/jcim-2013-0003. | Study design; Intervention/exposure
817 | Reichert, RG, Lyon, MR, Kacinik, V, Gahler, RJ, Manjoo, P, Purnama, M, Wood, S. Decreasing cardiovascular risk factors in obese individuals using a combination of PGX® meal replacements and PGX® granules in a 12-week clinical weight modification program. Journal of Complementary and Integrative Medicine. 2013. 10. doi:10.1515/jcim-2013-0003. | Study design; Intervention/exposure
818 | Reid, M, Hammersley, R, Duffy, M. Effects of sucrose drinks on macronutrient intake, body weight, and mood state in overweight women over 4 weeks. Appetite. 2010. 55:130-6. doi:10.1016/j.appet.2010.05.001. | Publication date (SSB published before 2012)
819 | Reid, M, Hammersley, R, Hill, AJ, Skidmore, P. Long-term dietary compensation for added sugar: effects of supplementary sucrose drinks over a 4-week period. Br J Nutr. 2007. 97:193-203. doi:10.1017/s0007114507252705. | Publication date
820 | Reidy, PT, Borack, MS, Markofski, MM, Dickinson, JM, Deer, RR, Husaini, SH, Walker, DK, Igbinigie, S, Robertson, SM, Cope, MB, Mukherjea, R, Hall-Porter, JM, Jennings, K, Volpi, E, Rasmussen, BB. Protein Supplementation Has Minimal Effects on Muscle Adaptations during Resistance Exercise Training in Young Men: A Double-Blind Randomized Clinical Trial. J Nutr. 2016. 146:1660-9. doi:10.3945/jn.116.231803. | Intervention/exposure; Comparator
821 | Reimer, R. Milk product intake: implications for weight control and type 2 diabetes. Can Nurse. 2008. 104:20. | Study design; Publication status
822 | Reinbach, HC, Smeets, A, Martinussen, T, Moller, P, Westerterp-Plantenga, MS. Effects of capsaicin, green tea and CH-19 sweet pepper on appetite and energy intake in humans in negative and positive energy balance. Clin Nutr. 2009. 28:260-5. doi:10.1016/j.clnu.2009.01.010. | Intervention/exposure; Comparator
823 | Reynolds, K, Wofford, MR, Chen, CS, Elmer, PJ, Myers, L, Chen, J, Whelton, PK, Jones, DW, He, J. Effect of dietary protein supplementation on body weight: a randomized controlled trial. Journal of diabetes. 2011. 3:215-216. doi:10.1111/j.1753-0407.2011.00122.x. | Publication status
824 | Rezvani, R, Cianflone, K, McGahan, JP, Berglund, L, Bremer, AA, Keim, NL, Griffen, SC, Havel, PJ, Stanhope, KL. Effects of sugar-sweetened beverages on plasma acylation stimulating protein, leptin and adiponectin: relationships with metabolic outcomes. Obesity (Silver Spring). 2013. 21:2471-80. doi:10.1002/oby.20437. | Other (e.g., duplicative data)
825 | Rhee, JJ, Qin, FF, Hedlin, HK, Chang, TI, Bird, CE, Zaslavsky, O, Manson, JE, Stefanick, ML, Winkelmayer, WC. Coffee and caffeine consumption and the risk of hypertension in postmenopausal women. American Journal of Clinical Nutrition. 2016. 103:210-217. doi:10.3945/ajcn.115.120147. | Outcome
826 | Ribeiro, C, Dourado, G, Cesar, T. Orange juice allied to a reduced-calorie diet results in weight loss and ameliorates obesity-related biomarkers: A randomized controlled trial. Nutrition. 2017. 38:13-19. doi:10.1016/j.nut.2016.12.020. | Intervention/exposure; Health status
827 | Ringel-Kulka, T, Kotch, JB, Jensen, ET, Savage, E, Weber, DJ. Randomized, double-blind, placebo-controlled study of synbiotic yogurt effect on the health of children. Journal of Pediatrics. 2015. 166:1475-1481.e3. doi:10.1016/j.jpeds.2015.02.038. | Population at Intervention/exposure
828 | Riso, P, Klimis-Zacas, D, Del Bo, C, Martini, D, Campolo, J, Vendrame, S, Moller, P, Loft, S, De Maria, R, Porrini, M. Effect of a wild blueberry (Vaccinium angustifolium) drink intervention on markers of oxidative stress, inflammation and endothelial function in humans with cardiovascular risk factors. Eur J Nutr. 2013. 52:949-61. doi:10.1007/s00394-012-0402-9. | Intervention/exposure; Comparator
829 | Ritchie, LD, Spector, P, Stevens, MJ, Schmidt, MM, Schreiber, GB, Striegel-Moore, RH, Wang, MC, Crawford, PB. Dietary patterns in adolescence are related to adiposity in young adulthood in black and white females. J Nutr. 2007. 137:399-406. doi:10.1093/jn/137.2.399. | Intervention/exposure
830 | Rito, AI, Carvalho, MA, Ramos, C, Breda, J. Program Obesity Zero (POZ)--a community-based intervention to address overweight primary-school children from five Portuguese municipalities. Public Health Nutr. 2013. 16:1043-51. doi:10.1017/s1368980013000244. | Intervention/exposure
831 | Robbins, KA, Wood, RA, Keet, CA. Milk allergy is associated with decreased growth in US children. J Allergy Clin Immunol. 2014. 134:1466-1468.e6. doi:10.1016/j.jaci.2014.08.037. | Study design
832 | Roberge, JB, Van Hulst, A, Barnett, TA, Drapeau, V, Benedetti, A, Tremblay, A, Henderson, M. Lifestyle Habits, Dietary Factors, and the Metabolically Unhealthy Obese Phenotype in Youth. J Pediatr. 2019. 204:46-52.e1. doi:10.1016/j.jpeds.2018.08.063. | Health status
833 | Roberts, R, Euiler, E, Ward, W, LeBlanc, P, Tarnopolsky, M, Roy, B. Higher intakes of low-fat milk combined with 12 weeks of endurance training does not result in lower fat mass and higher lean mass. FASEB journal. 2013. 27. | Publication status
834 | Robertson, J. Sweetened drinks and children’s health--what do we know, and what can we do?. Diabetes Technol Ther. 2003. 5:201-3. doi:10.1089/152091503321827867. | Study design
835 | Rockell, JE, Williams, SM, Taylor, RW, Grant, AM, Jones, IE, Goulding, A. Two-year changes in bone and body composition in young children with a history of prolonged milk avoidance. Osteoporos Int. 2005. 16:1016-23. doi:10.1007/s00198-004-1789-9. | Intervention/exposure
836 | Rodriguez-Cano, A, Mier-Cabrera, J, Balas-Nakash, M, Muñoz-Manrique, C, Legorreta-Legorreta, J, Perichart-Perera, O. Dietary changes associated with improvement of metabolic syndrome components in postmenopausal women receiving two different nutrition interventions. Menopause. 2015. 22:758-764. doi:10.1097/GME.0000000000000400. | Intervention/exposure; Outcome
837 | Rogers, I, Emmett, P, Gunnell, D, Dunger, D, Holly, J. Milk as a food for growth? The insulin-like growth factors link. Public Health Nutr. 2006. 9:359-68. | Study design
838 | Rohrer, JE, Takahashi, P. Should overweight and obese primary care patients be offered a meal replacement diet?. Obes Res Clin Pract. 2008. 2:I-ii. doi:10.1016/j.orcp.2008.08.002. | Intervention/exposure
839 | Roman, JL, Gonzalvez, ABM, Luque, A, Iglesias, JR, Hernandez, M, Villegas, JA. Physical activity and milk intake with conjugated linoleic acid (CLA) in healthy people with excess weight. Revista espanola de obesidad. 2007. 5:109-118. | Language
840 | Romero, AA, Duarte-Gardea, M, Ortiz, M, Labrado, C, Noe, M. Bone mineral density and body mass index of Mexican American Women. Hispanic Healthcare International. 2005. 3:9-14. | Outcome
841 | Ronco, AL, Stefani, ED, Mendoza, B, Deneo-Pellegrini, H, Vazquez, A, Abbona, E. Mate Intake and Risk of Breast Cancer in Uruguay: a Case- Control Study. Asian Pac J Cancer Prev. 2016. 17:1453-61. doi:10.7314/apjcp.2016.17.3.1453. | Outcome
842 | Rosa, FT, Freitas, EC, Deminice, R, Jordão, AA, Marchini, JS. Oxidative stress and inflammation in obesity after taurine supplementation: a double-blind, placebo-controlled study. European journal of nutrition. 2014. 53:823-830. doi:10.1007/s00394-013-0586-7. | Intervention/exposure
843 | Rosado, JL, Garcia, OP, Ronquillo, D, Hervert-Hernandez, D, Caamano Mdel, C, Martinez, G, Gutierrez, J, Garcia, S. Intake of milk with added micronutrients increases the effectiveness of an energy-restricted diet to reduce body weight: a randomized controlled clinical trial in Mexican women. J Am Diet Assoc. 2011. 111:1507-16. doi:10.1016/j.jada.2011.07.011. | Health status
844 | Rosengren, A, Dotevall, A, Wilhelmsen, L, Thelle, D, Johansson, S. Coffee and incidence of diabetes in Swedish women: a prospective 18-year follow-up study. J Intern Med. 2004. 255:89-95. | Outcome
845 | Rossi, F, Alberto, B, Jessica, C, Simona, B. Diets containing dairy foods positively affects weight and fat loss and cytokines blood levels in premenopausal obese women. Mediterranean Journal of Nutrition and Metabolism. 2015. 8:165-174. doi:10.3233/MNM-150035. | Health status
846 | Rothacker, DQ, Staniszewski, BA, Ellis, PK. Liquid meal replacement vs traditional food: a potential model for women who cannot maintain eating habit change. J Am Diet Assoc. 2001. 101:345-7. doi:10.1016/s0002-8223(01)00089-x. | Intervention/exposure
847 | Rothberg, AE, Ard, JD, Auriemma, A, Coburn, SL, Lewis, KH, Loper, J, Matarese, LE, Periman, S, Pories, WJ. Effect of total meal replacement program compared with a reduced-energy food-based diet plan on glycemic status-results from the optiwin study. Diabetes. 2018. 67:LB78-. | Publication status
848 | Ruel, G, Pomerleau, S, Couture, P, Lemieux, S, Lamarche, B, Couillard, C. Favourable impact of low-calorie cranberry juice consumption on plasma HDL-cholesterol concentrations in men. Br J Nutr. 2006. 96:357-64. | Study design
849 | Ruiz, JR. Metabolic syndrome and soft drink consumption. Ethnicity and Disease. 2009. 19:S321-S322. | Study design
850 | Rumpler, WV, Kramer, M, Rhodes, DG, Paul, DR. The impact of the covert manipulation of macronutrient intake on energy intake and the variability in daily food intake in nonobese men. Int J Obes (Lond). 2006. 30:774-81. doi:10.1038/sj.ijo.0803155. | Intervention/exposure; Comparator
851 | Rush, E, Paterson, J, Obolonkin, V. Food frequency information--relationships to body composition and apparent growth in 4-year-old children in the Pacific Island Family Study. N Z Med J. 2008. 121:63-71. | Study design
852 | Rush, E, Paterson, J, Obolonkin, V. Food frequency information-relationships to body composition and apparent growth in 4-year-old children in the Pacific Island Family Study. New Zealand Medical Journal. 2008. 121:63-71. | Study design; Duplicate
853 | Russo, MD, Ahrens, W, De Henauw, S, Eiben, G, Hebestreit, A, Kourides, Y, Lissner, L, Molnar, D, Moreno, LA, Pala, V, Veidebaum, T, Siani, A, Russo, P. The impact of adding sugars to milk and fruit on adiposity and diet quality in children: A cross-sectional and longitudinal analysis of the identification and prevention of dietary-and lifestyle-induced health effects in children and infants (IDEFICS) study. Nutrients. 2018. 10. doi:10.3390/nu10101350. | Intervention/exposure
854 | Saaksjarvi, K, Knekt, P, Rissanen, H, Laaksonen, MA, Reunanen, A, Mannisto, S. Prospective study of coffee consumption and risk of Parkinson’s disease. Eur J Clin Nutr. 2008. 62:908-15. doi:10.1038/sj.ejcn.1602788. | Outcome
855 | Saelens, BE, Couch, SC, Wosje, KS, Stark, LJ, Daniels, SR. Relations among milk and non-milk beverage consumption, calcium, and relative weight in high-weight status children. Journal of Clinical Psychology in Medical Settings. 2006. 13:117-125. doi:10.1007/s10880-006-9017-8. | Study design
856 | Saito, K, Obata, H, Nakamura, J, Fukui, N, Tanaka, T, Tonozuka, N. Body fat reducing effect and safety evaluation of long-term consumption of tea containing quercetin glucosides in obese subjects. Japanese pharmacology and therapeutics. 2014. 43:181-194. | Language
857 | Sakurai, M, Nakamura, K, Miura, K, Takamura, T, Yoshita, K, Nagasawa, SY, Morikawa, Y, Ishizaki, M, Kido, T, Naruse, Y, Suwazono, Y, Sasaki, S, Nakagawa, H. Sugar-sweetened beverage and diet soda consumption and the 7-year risk for type 2 diabetes mellitus in middle-aged Japanese men. Eur J Nutr. 2014. 53:251-8. doi:10.1007/s00394-013-0523-9. | Outcome
858 | Salazar-Martinez, E, Willett, WC, Ascherio, A, Manson, JE, Leitzmann, MF, Stampfer, MJ, Hu, FB. Coffee consumption and risk for type 2 diabetes mellitus. Ann Intern Med. 2004. 140:1-8. doi:10.7326/0003-4819-140-1-200401060-00005. | Outcome
859 | Sales, RL, Coelho, SB, Costa, NMB, Bressan, J, Iyer, S, Boateng, LA, Lokko, P, Mattes, RD. The effects of peanut oil on lipid profile of normolipidemic adults: A three-country collaborative study. Journal of Applied Research. 2008. 8:216-225. | Country
860 | Salinardi, TC, Rubin, KH, Black, RM, St-Onge, MP. Coffee mannooligosaccharides, consumed as part of a free-living, weight-maintaining diet, increase the proportional reduction in body volume in overweight men. J Nutr. 2010. 140:1943-8. doi:10.3945/jn.110.128207. | Comparator
861 | Samara, A, Herbeth, B, Ndiaye, NC, Fumeron, F, Billod, S, Siest, G, Visvikis-Siest, S. Dairy product consumption, calcium intakes, and metabolic syndrome-related factors over 5 years in the STANISLAS study. Nutrition. 2013. 29:519-24. doi:10.1016/j.nut.2012.08.013. | Intervention/exposure
862 | Santiago-Torres, M, Cui, Y, Adams, AK, Allen, DB, Carrel, AL, Guo, JY, Delgado-Rendon, A, LaRowe, TL, Schoeller, DA. Familial and individual predictors of obesity and insulin resistance in urban Hispanic children. Pediatr Obes. 2016. 11:54-60. doi:10.1111/ijpo.12020. | Study design
863 | Santiago-Torres, M, Cui, Y, Adams, AK, Allen, DB, Carrel, AL, Guo, JY, LaRowe, TL, Schoeller, DA. Structural equation modeling of the associations between the home environment and obesity-related cardiovascular fitness and insulin resistance among Hispanic children. Appetite. 2016. 101:23-30. doi:10.1016/j.appet.2016.02.003. | Study design
864 | Santos, LP, Ong, KK, Santos, IS, Matijasevich, A, Barros, AJD. Effects of dietary intake patterns from 1 to 4 years on BMI z-score and body shape at age of 6 years: a prospective birth cohort study from Brazil. Eur J Nutr. 2019. 58:1723-1734. doi:10.1007/s00394-018-1720-3. | Intervention/exposure
865 | Sari, FYK, Damayanthi, E, Kustiyah, L. The effect of rosella beverage intervention on lipid profileand antropometric in obese adult men. Indian Journal of Public Health Research and Development. 2018. 9:644-649. doi:10.5958/0976-5506.2018.01910.1. | Comparator; Country
866 | Sarma, KV, Udaykumar, P, Balakrishna, N, Vijayaraghavan, K, Sivakumar, B. Effect of micronutrient supplementation on health and nutritional status of schoolchildren: growth and morbidity. Nutrition. 2006. 22:S8-14. doi:10.1016/j.nut.2005.07.011. | Country
867 | Sarria, B, Martinez-Lopez, S, Sierra-Cinos, JL, Garcia-Diz, L, Mateos, R, Bravo-Clemente, L. Regularly consuming a green/roasted coffee blend reduces the risk of metabolic syndrome. Eur J Nutr. 2018. 57:269-278. doi:10.1007/s00394-016-1316-8. | Intervention/exposure
868 | Sartor, F, Donaldson, LF, Markland, DA, Loveday, H, Jackson, MJ, Kubis, HP. Taste perception and implicit attitude toward sweet related to body mass index and soft drink supplementation. Appetite. 2011. 57:237-46. doi:10.1016/j.appet.2011.05.107. | Study design; Comparator
869 | Sartor, F, Jackson, MJ, Squillace, C, Shepherd, A, Moore, JP, Ayer, DE, Kubis, HP. Adaptive metabolic response to 4 weeks of sugar-sweetened beverage consumption in healthy, lightly active individuals and chronic high glucose availability in primary human myotubes. Eur J Nutr. 2013. 52:937-48. doi:10.1007/s00394-012-0401-x. | Study design; Comparator
870 | Sasai, H, Ueda, K, Tsujimoto, T, Kobayashi, H, Sanbongi, C, Ikegami, S, Nakata, Y. Dose-ranging pilot randomized trial of amino acid mixture combined with physical activity promotion for reducing abdominal fat in overweight adults. Diabetes Metab Syndr Obes. 2017. 10:297-309. doi:10.2147/dmso.S138084. | Intervention/exposure
871 | Sazawal, S, Dhingra, U, Dhingra, P, Hiremath, G, Sarkar, A, Dutta, A, Menon, VP, Black, RE. Micronutrient fortified milk improves iron status, anemia and growth among children 1-4 years: A double masked, randomized, controlled trial. PLoS ONE. 2010. 5. doi:10.1371/journal.pone.0012167. | Country
872 | Sazawal, S, Dhingra, U, Hiremath, G, Sarkar, A, Dhingra, P, Dutta, A, Menon, VP, Black, RE. Effects of Bifidobacterium lactis HN019 and prebiotic oligosaccharide added to milk on iron status, anemia, and growth among children 1 to 4 years old. Journal of Pediatric Gastroenterology and Nutrition. 2010. 51:341-346. doi:10.1097/MPG.0b013e3181d98e45. | Country
873 | Scanlan, B, McTigue, KM, Wang, L, Winger, D, Conroy, MB. Association of eating habits with weight loss and diet self monitoring in an online weight loss trial: results from the OCELOT-PC study. Journal of general internal medicine.. 2015. 30:S105. | Publication status
874 | Schipp, D, Tulinska, J, Sustrova, M, Liskova, A, Spustova, V, Lehotska Mikusova, M, Krivosikova, Z, Rausova, K, Collins, A, Vebraite, V, Volkovova, K, Rollerova, E, Barancokova, M, Shaposhnikov, S. Consumption of a dark roast coffee blend reduces DNA damage in humans: results from a 4-week randomised controlled study. Eur J Nutr. 2018. . doi:10.1007/s00394-018-1863-2. | Intervention/exposure
875 | School anti-"fizzy drinks" programme helps to prevent obesity in children. Evidence-Based Healthcare and Public Health. 2004. 8:368-369. doi:10.1016/j.ehbc.2004.09.004. | Publication status
876 | Schoppen, S, Perez-Granados, AM, Carbajal, A, Oubina, P, Sanchez-Muniz, FJ, Gomez-Gerique, JA, Vaquero, MP. A sodium-rich carbonated mineral water reduces cardiovascular risk in postmenopausal women. J Nutr. 2004. 134:1058-63. doi:10.1093/jn/134.5.1058. | Study design; Comparator
877 | Schulz, V. Green tea extract for weight reduction? Randomized double blind study cannot confirm positive preliminary results. Zeitschrift fur phytotherapie. 2009. 30:74-75. doi:10.1055/s-0029-1222468. | Publication status; Language
878 | Schusdziarra, V, Hausmann, M, Wiedemann, C, Hess, J, Barth, C, Wagenpfeil, S, Erdmann, J. Successful weight loss and maintenance in everyday clinical practice with an individually tailored change of eating habits on the basis of food energy density. Eur J Nutr. 2011. 50:351-61. doi:10.1007/s00394-010-0143-6. | Study design; Intervention/exposure
879 | Schwab, U, Törrönen, A, Toppinen, L, Alfthan, G, Saarinen, M, Aro, A, Uusitupa, M. Betaine supplementation decreases plasma homocysteine concentrations but does not affect body weight, body composition, or resting energy expenditure in human subjects. American journal of clinical nutrition. 2002. 76:961-967. doi:10.1093/ajcn/76.5.961. | Intervention/exposure
880 | Schwartz, AE, Leardo, M, Aneja, S, Elbel, B. Effect of a School-Based Water Intervention on Child Body Mass Index and Obesity. JAMA Pediatr. 2016. 170:220-6. doi:10.1001/jamapediatrics.2015.3778. | Intervention/exposure
881 | Scott, HA, Gibson, PG, Garg, ML, Pretto, JJ, Morgan, PJ, Callister, R, Wood, LG. Determinants of weight loss success utilizing a meal replacement plan and/or exercise, in overweight and obese adults with asthma. Respirology. 2015. 20:243-50. doi:10.1111/resp.12423. | Intervention/exposure; Health status
882 | Seferidi, P, Millett, C, Laverty, AA. Sweetened beverage intake in association to energy and sugar consumption and cardiometabolic markers in children. Pediatr Obes. 2018. 13:195-203. doi:10.1111/ijpo.12194. | Study design
883 | Seimon, RV, Dodds, J, Muirhead, R, Zibellini, J, Das, A, Overs, S, Honeywood, J, Meroni, A, Fogelholm, M, Raben, A, etal, . Effect of an 8-week Low energy diet on muscle strength in adults with overweight and obesity-the PREVIEW study Australia. Obesity reviews. 2016. 17:168-. doi:10.1111/obr.12403. | Publication status
884 | Seki, S, Oda, Y, Shirakura, Y, Sakaguchi, H, Ueda, F, Fukuhara, I. Effects of composite supplements on obesity: a randomized, double-blind, placebo-controlled, parallel-group study. Japanese pharmacology and therapeutics. 2017. 45:957-966. | Language
885 | Setayeshgar, S, Whiting, SJ, Vatanparast, H. Prevalence of 10-year risk of cardiovascular diseases and associated risks in Canadian adults: The contribution of cardiometabolic risk assessment introduction. International Journal of Hypertension. 2013. 2013. doi:10.1155/2013/276564. | Study design; Outcome
886 | Sharp, MH, Lowery, RP, Shields, KA, Lane, JR, Gray, JL, Partl, JM, Hayes, DW, Wilson, GJ, Hollmer, CA, Minivich, JR, Wilson, JM. The Effects of Beef, Chicken, or Whey Protein After Workout on Body Composition and Muscle Performance. J Strength Cond Res. 2018. 32:2233-2242. doi:10.1519/jsc.0000000000001936. | Comparator
887 | Shashaj, B, Graziani, MP, Contoli, B, Ciuffo, C, Cives, C, Facciolini, S, Rigoni, ML, Spaterna, S, Taucci, M, Raponi, M, Manco, M. Energy Balance-Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers. J Am Coll Nutr. 2016. 35:362-71. doi:10.1080/07315724.2015.1070699. | Study design; Duplicate
888 | Shashaj, B, Graziani, MP, Contoli, B, Ciuffo, C, Cives, C, Facciolini, S, Rigoni, ML, Spaterna, S, Taucci, M, Raponi, M, Manco, M. Energy Balance–Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers. Journal of the American College of Nutrition. 2016. 35:362-371. doi:10.1080/07315724.2015.1070699. | Study design
889 | Sheikholeslami Vatani, D, Ahmadi Kani Golzar, F. Changes in antioxidant status and cardiovascular risk factors of overweight young men after six weeks supplementation of whey protein isolate and resistance training. Appetite. 2012. 59:673-8. doi:10.1016/j.appet.2012.08.005. | Comparator
890 | Shen, CL, Chyu, MC, Yeh, JK, Zhang, Y, Pence, BC, Felton, CK, Dagda, RY, Dagda, M, Doctolero, S, Flores, MJ, etal, . Green tea polyphenols and Tai Chi exercise for postmenopausal osteopenic women: safety report from a 24-week placebo-controlled randomized trial. FASEB journal. 2010. 24. | Publication status
891 | Shenoy, SF, Poston, WS, Reeves, RS, Kazaks, AG, Holt, RR, Keen, CL, Chen, HJ, Haddock, CK, Winters, BL, Khoo, CS, Foreyt, JP. Weight loss in individuals with metabolic syndrome given DASH diet counseling when provided a low sodium vegetable juice: a randomized controlled trial. Nutr J. 2010. 9:8. doi:10.1186/1475-2891-9-8. | Health status
892 | Shetty, P, Mooventhan, A, Nagendra, HR. Does short-term lemon honey juice fasting have effect on lipid profile and body composition in healthy individuals?. J Ayurveda Integr Med. 2016. 7:11-3. doi:10.1016/j.jaim.2016.03.001. | Comparator; Country
893 | Sialvera, TE, Pounis, GD, Koutelidakis, AE, Richter, DJ, Yfanti, G, Kapsokefalou, M, Goumas, G, Chiotinis, N, Diamantopoulos, E, Zampelas, A. Phytosterols supplementation decreases plasma small and dense LDL levels in metabolic syndrome patients on a westernized type diet. Nutrition, Metabolism and Cardiovascular Diseases. 2012. 22:843-848. doi:10.1016/j.numecd.2010.12.004. | Comparator
894 | Sichieri, R, Paula Trotte, A, de Souza, RA, Veiga, GV. School randomised trial on prevention of excessive weight gain by discouraging students from drinking sodas. Public Health Nutr. 2009. 12:197-202. doi:10.1017/s1368980008002644. | Intervention/exposure; Comparator
895 | Silva, DR, Ohara, D, Tomeleri, CM, Batista, MB, Fernandes, RA, Ronque, ER, Sardinha, LB, Cyrino, ES. Association between risk behaviors and adiposity indicators in adolescents from Southern Brazil: A methodological approach. J Child Health Care. 2016. 20:314-23. doi:10.1177/1367493515598642. | Study design
896 | Silveira, JQ, Dourado, GK, Cesar, TB. Red-fleshed sweet orange juice improves the risk factors for metabolic syndrome. Int J Food Sci Nutr. 2015. 66:830-6. doi:10.3109/09637486.2015.1093610. | Study design
897 | Silver, HJ, Dietrich, MS, Niswender, KD. Effects of grapefruit, grapefruit juice and water preloads on energy balance, weight loss, body composition, and cardiometabolic risk in free-living obese adults. Nutr Metab (Lond). 2011. 8:8. doi:10.1186/1743-7075-8-8. | Health status
898 | Simbo, S, Kim, H, Chrown, J, Roque, A, Banerjee, N, Talcott, S, Kreider, R, Mertens-Talcott, S. Consumption of acai beverage (Euterpe oleracea Mart.) In cardiometabolic syndrome. FASEB journal. 2015. 29. | Publication status
899 | Simpson, EJ, Mendis, B, Macdonald, IA. Orange juice consumption and its effect on blood lipid profile and indices of the metabolic syndrome; a randomised, controlled trial in an at-risk population. Food Funct. 2016. 7:1884-91. doi:10.1039/c6fo00039h. | Comparator
900 | Singh, AS, Chin, APawMJ, Brug, J, van Mechelen, W. Dutch obesity intervention in teenagers: effectiveness of a school-based program on body composition and behavior. Arch Pediatr Adolesc Med. 2009. 163:309-17. doi:10.1001/archpediatrics.2009.2. | Intervention/exposure
901 | Singh, AS, Chinapaw, MJ, Brug, J, Kremers, SP, Visscher, TL, van Mechelen, W. Correction: Ethnic differences in BMI among Dutch adolescents: what is the role of screen viewing, active commuting to school, and consumption of soft drinks and high-caloric snacks?. Int J Behav Nutr Phys Act. 2009. 6:40. doi:10.1186/1479-5868-6-40. | Study design
902 | Skinner, JD, Bounds, W, Carruth, BR, Ziegler, P. Longitudinal calcium intake is negatively related to children’s body fat indexes. J Am Diet Assoc. 2003. 103:1626-31. doi:10.1016/j.jada.2003.09.018. | Intervention/exposure
903 | Skop-Lewandowska, A, Zajac, J, Kolarzyk, E. Overweight and obesity vs. simple carbohydrates consumption by elderly people suffering from diseases of the cardiovascular system. Ann Agric Environ Med. 2017. 24:575-580. doi:10.5604/12321966.1233555. | Study design; Health status
904 | Sluijs, I, Forouhi, NG, Beulens, JW, van der Schouw, YT, Agnoli, C, Arriola, L, Balkau, B, Barricarte, A, Boeing, H, Bueno-de-Mesquita, HB, Clavel-Chapelon, F, Crowe, FL, de Lauzon-Guillain, B, Drogan, D, Franks, PW, Gavrila, D, Gonzalez, C, Halkjaer, J, Kaaks, R, Moskal, A, Nilsson, P, Overvad, K, Palli, D, Panico, S, Quiros, JR, Ricceri, F, Rinaldi, S, Rolandsson, O, Sacerdote, C, Sanchez, MJ, Slimani, N, Spijkerman, AM, Teucher, B, Tjonneland, A, Tormo, MJ, Tumino, R, van der, Dl A, Sharp, SJ, Langenberg, C, Feskens, EJ, Riboli, E, Wareham, NJ. The amount and type of dairy product intake and incident type 2 diabetes: results from the EPIC-InterAct Study. Am J Clin Nutr. 2012. 96:382-90. doi:10.3945/ajcn.111.021907. | Outcome
905 | Smilowitz, JT, Wiest, MM, Teegarden, D, Zemel, MB, German, JB, Van Loan, MD. Dietary fat and not calcium supplementation or dairy product consumption is associated with changes in anthropometrics during a randomized, placebo-controlled energy-restriction trial. Nutrition & metabolism. 2011. 8. doi:10.1186/1743-7075-8-67. | Intervention/exposure
906 | Smith, AD, Emmett, PM, Newby, PK, Northstone, K. Dietary patterns and changes in body composition in children between 9 and 11 years. Food Nutr Res. 2014. 58. doi:10.3402/fnr.v58.22769. | Intervention/exposure
907 | Smith, B, Wingard, DL, Smith, TC, Kritz-Silverstein, D, Barrett-Connor, E. Does coffee consumption reduce the risk of type 2 diabetes in individuals with impaired glucose?. Diabetes Care. 2006. 29:2385-90. doi:10.2337/dc06-1084. | Outcome
908 | Smith, GI, Commean, PK, Reeds, DN, Klein, S, Mittendorfer, B. Effect of Protein Supplementation During Diet-Induced Weight Loss on Muscle Mass and Strength: A Randomized Controlled Study. Obesity (Silver Spring). 2018. 26:854-861. doi:10.1002/oby.22169. | Intervention/exposure
909 | Smith, LH, Laurent, D, Baumker, E, Petosa, RL. Rates of Obesity and Obesogenic Behaviors of Rural Appalachian Adolescents: How Do They Compare to Other Adolescents or Recommendations?. J Phys Act Health. 2018. 15:874-881. doi:10.1123/jpah.2017-0602. | Study design; Intervention/exposure
910 | Smith, TJ, Sigrist, LD, Bathalon, GP, McGraw, S, Karl, JP, Young, AJ. Efficacy of a meal-replacement program for promoting blood lipid changes and weight and body fat loss in US Army soldiers. J Am Diet Assoc. 2010. 110:268-73. doi:10.1016/j.jada.2009.10.039. | Intervention/exposure
911 | Smith-Ryan, AE, Hirsch, KR, Blue, MNM, Mock, MG, Trexler, ET. High-Fat Breakfast Meal Replacement in Overweight and Obesity: Implications on Body Composition, Metabolic Markers, and Satiety. Nutrients. 2019. 11. doi:10.3390/nu11040865. | Intervention/exposure
912 | So soft drinks contribute to obesity?. Child Health Alert. 2003. 21:1. | Study design; Publication status
913 | Soedamah-Muthu, SS, Masset, G, Verberne, L, Geleijnse, JM, Brunner, EJ. Consumption of dairy products and associations with incident diabetes, CHD and mortality in the Whitehall II study. Br J Nutr. 2013. 109:718-26. doi:10.1017/s0007114512001845. | Outcome
914 | Soenen, S, Hochstenbach-Waelen, A, Westerterp-Plantenga, MS. Efficacy of ?-lactalbumin and milk protein on weight loss and body composition during energy restriction. Obesity (silver spring, md.). 2011. 19:370-379. | Intervention/exposure; Duplicate
915 | Soenen, S, Hochstenbach-Waelen, A, Westerterp-Plantenga, MS. Efficacy of alpha-lactalbumin and milk protein on weight loss and body composition during energy restriction. Obesity (Silver Spring). 2011. 19:370-9. doi:10.1038/oby.2010.146. | Intervention/exposure
916 | Soenen, S, Hochstenbach-Waelen, A, Westerterp-Plantenga, MS. Efficacy of α-lactalbumin and milk protein on weight loss and body composition during energy restriction. Obesity. 2011. 19:370-379. doi:10.1038/oby.2010.146. | Intervention/exposure; Comparator
917 | Soerensen, KV, Thorning, TK, Astrup, A, Kristensen, M, Lorenzen, JK. Effect of dairy calcium from cheese and milk on fecal fat excretion, blood lipids, and appetite in young men. Am J Clin Nutr. 2014. 99:984-91. doi:10.3945/ajcn.113.077735. | Outcome
918 | Solah, VA, Kerr, DA, Hunt, WJ, Johnson, SK, Boushey, CJ, Delp, EJ, Meng, X, Gahler, RJ, James, AP, Mukhtar, AS, Fenton, HK, Wood, S. Effect of Fibre Supplementation on Body Weight and Composition, Frequency of Eating and Dietary Choice in Overweight Individuals. Nutrients. 2017. 9. doi:10.3390/nu9020149. | Intervention/exposure
919 | Soltero, SM, Palacios, C. Association between dietary patterns and body composition in a group or Puerto Rican obese adults: a pilot study. P R Health Sci J. 2011. 30:22-7. | Study design; Health status
920 | Sone, T, Kuriyama, S, Nakaya, N, Hozawa, A, Shimazu, T, Nomura, K, Rikimaru, S, Tsuji, I. Randomized controlled trial for an effect of catechin-enriched green tea consumption on adiponectin and cardiovascular disease risk factors. Food Nutr Res. 2011. 55. doi:10.3402/fnr.v55i0.8326. | Comparator
921 | Song, MY, Bose, S, Kim, HJ, Lee, MJ, Lim, CY. The impact of Ephedra and green tea combination mesotherapy on localized fat: A randomized-controlled clinical trial. European Journal of Integrative Medicine. 2012. 4:e323-e334. doi:10.1016/j.eujim.2012.03.002. | Intervention/exposure
922 | Springer, AE, Kelder, SH, Byrd-Williams, CE, Pasch, KE, Ranjit, N, Delk, JE, Hoelscher, DM. Promoting energy-balance behaviors among ethnically diverse adolescents: overview and baseline findings of The Central Texas CATCH Middle School Project. Health Educ Behav. 2013. 40:559-70. doi:10.1177/1090198112459516. | Intervention/exposure
923 | Stanhope, KL, Griffen, SC, Bremer, AA, Vink, RG, Schaefer, EJ, Nakajima, K, Schwarz, JM, Beysen, C, Berglund, L, Keim, NL, Havel, PJ. Metabolic responses to prolonged consumption of glucose- and fructose-sweetened beverages are not associated with postprandial or 24-h glucose and insulin excursions. American Journal of Clinical Nutrition. 2011. 94:112-119. doi:10.3945/ajcn.110.002246. | Outcome; Other (e.g., duplicative data)
924 | Stanhope, KL, Schwarz, JM, Keim, NL, Griffen, SC, Bremer, AA, Graham, JL, Hatcher, B, Cox, CL, Dyachenko, A, Zhang, W, McGahan, JP, Seibert, A, Krauss, RM, Chiu, S, Schaefer, EJ, Ai, M, Otokozawa, S, Nakajima, K, Nakano, T, Beysen, C, Hellerstein, MK, Berglund, L, Havel, PJ. Consuming fructose-sweetened, not glucose-sweetened, beverages increases visceral adiposity and lipids and decreases insulin sensitivity in overweight/obese humans. J Clin Invest. 2009. 119:1322-34. doi:10.1172/jci37385. | Comparator
925 | Stastny, SN, Christensen, BK, Greterman, SH, Okamatsu, H, Manikowske, TL, Youd, L, Champa, J. The effect of creatine supplementation with milk combined with resistance training on strength and power in women. Gazzetta Medica Italiana Archivio per le Scienze Mediche. 2015. 174:209-224. | Comparator; Language
926 | Stendell-Hollis, NR, Thomson, CA, Thompson, PA, Bea, JW, Cussler, EC, Hakim, IA. Green tea improves metabolic biomarkers, not weight or body composition: a pilot study in overweight breast cancer survivors. J Hum Nutr Diet. 2010. 23:590-600. doi:10.1111/j.1365-277X.2010.01078.x. | Comparator
927 | Stettler, N, Wrotniak, BH, Hill, DL, Kumanyika, SK, Xanthopoulos, MS, Nihtianova, S, Shults, J, Leff, SS, Pinto, A, Berkowitz, RI, Faith, MS. Prevention of excess weight gain in paediatric primary care: beverages only or multiple lifestyle factors. The Smart Step Study, a cluster-randomized clinical trial. Pediatr Obes. 2015. 10:267-74. doi:10.1111/ijpo.260. | Intervention/exposure; Comparator
928 | Stettler, N, Wrotniak, BH, Hill, DL, Kumanyika, SK, Xanthopoulos, MS, Nihtianova, S, Shults, J, Leff, SS, Pinto, A, Berkowitz, RI, Faith, MS. Prevention of excess weight gain in paediatric primary care: Beverages only or multiple lifestyle factors. the Smart Step Study, a cluster-randomized clinical trial. Pediatric Obesity. 2014. 10:267-274. doi:10.1111/ijpo.260. | Intervention/exposure
929 | Steurer, J. Drinking water before eating promotes weight loss. Praxis. 2016. 105:107-108. doi:10.1024/1661-8157/a002254. | Language
930 | Stojkovic, V, Simpson, CA, Sullivan, RR, Cusano, AM, Kerstetter, JE, Kenny, AM, Insogna, KL, Bihuniak, JD. The Effect of Dietary Glycemic Properties on Markers of Inflammation, Insulin Resistance, and Body Composition in Postmenopausal American Women: An Ancillary Study from a Multicenter Protein Supplementation Trial. Nutrients. 2017. 9. doi:10.3390/nu9050484. | Intervention/exposure
931 | St-Onge, MP, Goree, LL, Gower, B. High-milk supplementation with healthy diet counseling does not affect weight loss but ameliorates insulin action compared with low-milk supplementation in overweight children. J Nutr. 2009. 139:933-8. doi:10.3945/jn.108.102079. | Health status
932 | St-Onge, MP, Salinardi, T, Herron-Rubin, K, Black, RM. A weight-loss diet including coffee-derived mannooligosaccharides enhances adipose tissue loss in overweight men but not women. Obesity (Silver Spring). 2012. 20:343-8. doi:10.1038/oby.2011.289. | Intervention/exposure
933 | Stookey, JD, Constant, F, Gardner, CD, Popkin, BM. Replacing sweetened caloric beverages with drinking water is associated with lower energy intake. Obesity (Silver Spring). 2007. 15:3013-22. doi:10.1038/oby.2007.359. | Outcome
934 | Stookey, JD, Constant, F, Popkin, BM, Gardner, CD. Drinking water is associated with weight loss in overweight dieting women independent of diet and activity. Obesity (Silver Spring). 2008. 16:2481-8. doi:10.1038/oby.2008.409. | Intervention/exposure
935 | Stookey, JD, Del Toro, R, Hamer, J, Medina, A, Higa, A, Ng, V, TinajeroDeck, L, Juarez, L. Qualitative and/or quantitative drinking water recommendations for pediatric obesity treatment. J Obes Weight Loss Ther. 2014. 4:232. doi:10.4172/2165-7904.1000232. | Intervention/exposure; Comparator
936 | Strand, MA, Perry, J, Wang, P, Liu, S, Lynn, H. Risk factors for metabolic syndrome in a cohort study in a north China urban middle-aged population. Asia Pac J Public Health. 2015. 27:Np255-65. doi:10.1177/1010539512438609. | Study design; Outcome
937 | Suder, A, Janusz, M, Jagielski, P, Glodzik, J, Palka, T, Cison, T, Pilch, W. Prevalence and risk factors of abdominal obesity in Polish rural children. Homo. 2015. 66:357-68. doi:10.1016/j.jchb.2014.09.008. | Study design
938 | Sugihara Junior, P, Ribeiro, AS, Nabuco, HCG, Fernandes, RR, Tomeleri, CM, Cunha, PM, Venturini, D, Barbosa, DS, Schoenfeld, BJ, Cyrino, ES. Effects of Whey Protein Supplementation Associated With Resistance Training on Muscular Strength, Hypertrophy, and Muscle Quality in Preconditioned Older Women. Int J Sport Nutr Exerc Metab. 2018. 28:528-535. doi:10.1123/ijsnem.2017-0253. | Intervention/exposure
939 | Sugimori, H, Yoshida, K, Izuno, T, Miyakawa, M, Suka, M, Sekine, M, Yamagami, T, Kagamimori, S. Analysis of factors that influence body mass index from ages 3 to 6 years: A study based on the Toyama cohort study. Pediatr Int. 2004. 46:302-10. doi:10.1111/j.1442-200x.2004.01895.x. | Study design
940 | Suglia, SF, Duarte, CS, Chambers, EC, Boynton-Jarrett, R. Social and behavioral risk factors for obesity in early childhood. J Dev Behav Pediatr. 2013. 34:549-56. doi:10.1097/DBP.0b013e3182a509c0. | Study design
941 | Suliga, E, Adamczyk-Gruszka, OK. Health behaviours of pregnant women and gestational weight gains -A pilot study. Medical Studies/Studia Medyczne. 2015. 31:161-167. doi:10.5114/ms.2015.54753. | Study design
942 | Summaries for patients. The relationship between green tea intake and type 2 diabetes in Japanese adults. Ann Intern Med. 2006. 144:I28. doi:10.7326/0003-4819-144-8-200604180-00001. | Study design
943 | Sumridddetchkajorn, K, Winichagoon, P, Kriengsinyos, W, Sangkanuparph, S. Effects of increased caloric intake on resting energy expenditure, body composition, blood lipid levels and insulin resistance in patients on HAART. Clinical nutrition, supplement.. 2011. 6:86-87. | Publication status
944 | Surono, IS, Koestomo, FP, Novitasari, N, Zakaria, FR, Yulianasari, , Koesnandar, . Novel probiotic Enterococcus faecium IS-27526 supplementation increased total salivary sIgA level and bodyweight of pre-school children: a pilot study. Anaerobe. 2011. 17:496-500. doi:10.1016/j.anaerobe.2011.06.003. | Country
945 | Sutehall, S, Muniz-Pardos, B, Bosch, AN, Di Gianfrancesco, A, Pitsiladis, YP. Sports drinks on the edge of a new era. Current Sports Medicine Reports. 2018. 17:112-116. doi:10.1249/JSR.0000000000000475. | Study design
946 | Suzuki, Y, Nozawa, A, Miyamoto, S, Sagesaka, YM, Azuma, M, Kajimoto, Y, Nishitani, M. Reduction of visceral fat in overweight female volunteers by long-term ingestion of tea catechins with a galloyl moiety - A randomized double-blind placebo-controlled study. Japanese pharmacology and therapeutics. 2009. 37:521-527. | Language
947 | Swarbrick, MM, Stanhope, KL, Elliott, SS, Graham, JL, Krauss, RM, Christiansen, MP, Griffen, SC, Keim, NL, Havel, PJ. Consumption of fructose-sweetened beverages for 10 weeks increases postprandial triacylglycerol and apolipoprotein-B concentrations in overweight and obese women. Br J Nutr. 2008. 100:947-52. doi:10.1017/s0007114508968252. | Study design
948 | Sweetened drinks raise women’s risk for obesity, type 2 diabetes. Harvard women’s health watch. 2004. 12:6. | Study design; Publication status
949 | Szulinska, M, Bogdanski, P, Musialik, K, Suliburska, J. Beneficial influence of green tea extract supplementation on blood pressure, insulin resistance, selected inflammatory markers and total antioxidant status in patients with obesity related hypertension. Obesity facts.. 2012. 5:197. doi:10.1159/000258190. | Publication status
950 | Tada, Y, Kawano, Y, Maeda, I, Yoshizaki, T, Sunami, A, Yokoyama, Y, Matsumoto, H, Hida, A, Komatsu, T, Togo, F. Association of body mass index with lifestyle and rotating shift work in Japanese female nurses. Obesity (Silver Spring). 2014. 22:2489-93. doi:10.1002/oby.20908. | Study design
951 | Tahavorgar, A, Vafa, M, Shidfar, F, Gohari, M, Heydari, I. Whey protein preloads are more beneficial than soy protein preloads in regulating appetite, calorie intake, anthropometry, and body composition of overweight and obese men. Nutr Res. 2014. 34:856-61. doi:10.1016/j.nutres.2014.08.015. | Comparator
952 | Takahashi, M, Miyashita, M, Suzuki, K, Bae, SR, Kim, HK, Wakisaka, T, Matsui, Y, Takeshita, M, Yasunaga, K. Acute ingestion of catechin-rich green tea improves postprandial glucose status and increases serum thioredoxin concentrations in postmenopausal women. British Journal of Nutrition. 2014. 112:1542-1550. doi:10.1017/S0007114514002530. | Intervention/exposure; Comparator
953 | Takahira, M, Noda, K, Fukushima, M, Zhang, B, Mitsutake, R, Uehara, Y, Ogawa, M, Kakuma, T, Saku, K. Randomized, double-blind, controlled, comparative trial of formula food containing soy protein vs. milk protein in visceral fat obesity. -FLAVO study. Circ J. 2011. 75:2235-43. | Intervention/exposure; Comparator
954 | Takahira, M, Noda, K, Fukushima, M, Zhang, B, Mitsutake, R, Uehara, Y, Ogawa, M, Kakuma, T, Saku, K. Randomized, double-blind, controlled, comparative trial of formula food containing soy protein vs. milk protein in visceral fat obesity: FLAVO Study. Circulation Journal. 2011. 75:2235-2243. doi:10.1253/circj.CJ-10-1013. | Comparator
955 | Takase, H, Nagao, T, Otsuka, K, Kozuma, K, Kataoka, K, Meguro, S, Komikado, M, Tokimitsu, I. Effects of long-term ingestion of tea catechins on visceral fat accumulation and metabolic syndrome: pooling-analysis of 7 randomized controlled trials. Japanese pharmacology and therapeutics. 2008. 36:509-514. | Language
956 | Takase, H, Nagao, T, Otsuka, K, Meguro, S, Komikado, M, Tokimitsu, I. Effects of long-term ingestion of tea catechins on visceral fat accumulation and metabolic syndrome risk in women with abdominal obesity. Japanese pharmacology and therapeutics. 2008. 36:237-245. | Language
957 | Takcda, R, Miyata, S, Hashimoto, K, Sato, K, Kanda, T. Reducing effect of apple polyphenols beverage consumption on human body fat. Japanese pharmacology and therapeutics. 2017. 45:635-651. | Language
958 | Takeda, E, Yamanaka-Okumura, H, Taketani, Y, Inagaki, N, Hosokawa, M, Shide, K, Maegawa, H, Kondo, K, Kawasaki, E, Shinozaki, S, Fujinaka, Y, Matsubara, T, Katayama, T, Sasaki, H, Kawashima, A, Aonuma, H. Effect of nutritional counseling and long term isomaltulose based liquid formula (MHN-01) intake on metabolic syndrome. Journal of Clinical Biochemistry and Nutrition. 2015. 57:140-144. doi:10.3164/JCBN.14-132. | Intervention/exposure; Comparator
959 | Takeshita, M, Otsuka, K, Yasunaga, K, Katsuragi, Y. Green tea catechin consumption affects metabolic syndrome in Japanese overweight and obese adults. Circulation. 2013. 128. | Publication status
960 | Takeshita, M, Takase, H, Otsuka, K, Katashima, M, Yasunaga, K, Yasumasu, T. A catechin-rich beverage with no caffeine ameliorates body fat and circulating high-molecular weight adiponectin (HMW-AD) in overweight/obese men. #journal#. 2010. . | Publication status
961 | Takeshita, M, Takashima, S, Harada, U, Shibata, E, Hosoya, N, Takase, H, Otsuka, K, Meguro, S, Komikado, M, Tokimitsu, I. Effects of long-term consumption of tea catechins-enriched beverage with no caffeine on body composition in humans. Japanese pharmacology and therapeutics. 2008. 36:767-776. | Language
962 | Takomana, G, Kalimbira, AA. Weight gain, physical activity and dietary changes during the seven months of first-year university life in Malawi. South African Journal of Clinical Nutrition. 2012. 25:132-139. doi:10.1080/16070658.2012.11734417. | Country
963 | Tam, CS, Garnett, SP, Cowell, CT, Campbell, K, Cabrera, G, Baur, LA. Soft drink consumption and excess weight gain in Australian school students: results from the Nepean study. Int J Obes (Lond). 2006. 30:1091-3. doi:10.1038/sj.ijo.0803328. | Publication date
964 | Tanaka, K, Yuasa, M, Yamamoto, S, Omagari, K, Miyata, Y, Tanaka, T, Tamaya, K, Yoshino, Y, Ono, H, Maru, I, etal, . Effects of fermented tea leaves made by tea-rolling processing of loquat leaves and third crop green tea leaves on visceral fat - A randomized, double-blind, placebo-controlled, parallel-group comparative study. Japanese pharmacology and therapeutics. 2018. 46:539-547. | Language
965 | Tanaka, S, Uenishi, K, Ishida, H, Takami, Y, Hosoi, T, Kadowaki, T, Orimo, H, Ohashi, Y. A randomized intervention trial of 24-wk dairy consumption on waist circumference, blood pressure, and fasting blood sugar and lipids in Japanese men with metabolic syndrome. J Nutr Sci Vitaminol (Tokyo). 2014. 60:305-12. doi:10.3177/jnsv.60.305. | Intervention/exposure
966 | Tanaka, S, Uenishi, K, Ishida, H, Takami, Y, Hosoi, T, Kadowaki, T, Orimo, H, Ohashi, Y. A randomized intervention trial of 24-wk dairy consumption on waist circumference, blood pressure, and fasting blood sugar and lipids in Japanese men with metabolic syndrome. Journal of Nutritional Science and Vitaminology. 2015. 60:305-312. | Intervention/exposure
967 | Tate, DF, Turner-McGrievy, G, Stevens, J, Erickson, K, Polzien, K, Diamond, M, Popkin, BM. Replacing caloric beverages with water or diet beverages for weight loss in adults: results of a 6-month randomized controlled trial. Obesity (silver spring, md.). 2011. 19:S68-. doi:10.1038/oby.2011.222. | Publication status
968 | Tatone-Tokuda, F, Dubois, L, Ramsay, T, Girard, M, Touchette, E, Petit, D, Montplaisir, JY. Sex differences in the association between sleep duration, diet and body mass index: a birth cohort study. J Sleep Res. 2012. 21:448-60. doi:10.1111/j.1365-2869.2011.00989.x. | Intervention/exposure
969 | Taveras, EM, Gillman, MW, Kleinman, KP, Rich-Edwards, JW, Rifas-Shiman, SL. Reducing racial/ethnic disparities in childhood obesity: the role of early life risk factors. JAMA Pediatr. 2013. 167:731-8. doi:10.1001/jamapediatrics.2013.85. | Intervention/exposure
970 | Taveras, EM, Gortmaker, SL, Hohman, KH, Horan, CM, Kleinman, KP, Mitchell, K, Price, S, Prosser, LA, Rifas-Shiman, SL, Gillman, MW. Randomized controlled trial to improve primary care to prevent and manage childhood obesity: the High Five for Kids study. Arch Pediatr Adolesc Med. 2011. 165:714-22. doi:10.1001/archpediatrics.2011.44. | Intervention/exposure
971 | Taylor, LW, Wilborn, C, Roberts, MD, White, A, Dugan, K. Eight weeks of pre- and postexercise whey protein supplementation increases lean body mass and improves performance in Division III collegiate female basketball players. Appl Physiol Nutr Metab. 2016. 41:249-54. doi:10.1139/apnm-2015-0463. | Intervention/exposure
972 | Taylor, RW, McAuley, KA, Barbezat, W, Strong, A, Williams, SM, Mann, JI. APPLE Project: 2-y findings of a community-based obesity prevention program in primary school age children. Am J Clin Nutr. 2007. 86:735-42. doi:10.1093/ajcn/86.3.735. | Intervention/exposure
973 | Taylor, RW, McAuley, KA, Barbezat, W, Strong, A, Williams, SM, Mann, JI. APPLE Project: 2-y findings of a community-based obesity prevention program in primary school-age children. American Journal of Clinical Nutrition. 2007. 86:735-742. | Intervention/exposure
974 | Ten Haaf, DSM, Eijsvogels, TMH, Bongers, Ccwg, Horstman, AMH, Timmers, S, de Groot, Lcpgm, Hopman, MTE. Protein supplementation improves lean body mass in physically active older adults: a randomized placebo-controlled trial. J Cachexia Sarcopenia Muscle. 2019. 10:298-310. doi:10.1002/jcsm.12394. | Comparator
975 | Teshima, N, Shimo, M, Miyazawa, K, Konegawa, S, Matsumoto, A, Onishi, Y, Sasaki, R, Suzuki, T, Yano, Y, Matsumoto, K, Yamada, T, Gabazza, EC, Takei, Y, Sumida, Y. Effects of sugar-sweetened beverage intake on the development of type 2 diabetes mellitus in subjects with impaired glucose tolerance: the Mihama diabetes prevention study. J Nutr Sci Vitaminol (Tokyo). 2015. 61:14-9. doi:10.3177/jnsv.61.14. | Outcome
976 | Theim, KR, Brown, JD, Juarascio, AS, Malcolm, RR, O’Neil, PM. Relations of hedonic hunger and behavioral change to weight loss among adults in a behavioral weight loss program utilizing meal-replacement products. Behav Modif. 2013. 37:790-805. doi:10.1177/0145445513501319. | Study design; Intervention/exposure
977 | Thom, E. The effect of chlorogenic acid enriched coffee on glucose absorption in healthy volunteers and its effect on body mass when used long-term in overweight and obese people. J Int Med Res. 2007. 35:900-8. doi:10.1177/147323000703500620. | Comparator
978 | Thomas, DT, Wideman, L, Lovelady, CA. Effects of a dairy supplement and resistance training on lean mass and insulin-like growth factor in women. Int J Sport Nutr Exerc Metab. 2011. 21:181-8. | Intervention/exposure
979 | Thompson, OM, Ballew, C, Resnicow, K, Must, A, Bandini, LG, Cyr, H, Dietz, WH. Food purchased away from home as a predictor of change in BMI z-score among girls. Int J Obes Relat Metab Disord. 2004. 28:282-9. doi:10.1038/sj.ijo.0802538. | Intervention/exposure
980 | Thomson, RL, Brinkworth, GD, Noakes, M, Buckley, JD. Muscle strength gains during resistance exercise training are attenuated with soy compared with dairy or usual protein intake in older adults: a randomized controlled trial. Clinical nutrition (edinburgh, scotland). 2016. 35:27-33. doi:10.1016/j.clnu.2015.01.018. | Intervention/exposure
981 | Tian, C, Huang, Q, Yang, L, Legare, S, Angileri, F, Yang, H, Li, X, Min, X, Zhang, C, Xu, C, Yuan, J, Miao, X, He, MA, Wu, T, Zhang, X. Green tea consumption is associated with reduced incident CHD and improved CHD-related biomarkers in the Dongfeng-Tongji cohort. Sci Rep. 2016. 6:24353. doi:10.1038/srep24353. | Outcome
982 | Tian, X, Huang, Y, Wang, H. Deviation of Chinese Adults’ Diet from the Chinese Food Pagoda 2016 and Its Association with Adiposity. Nutrients. 2017. 9. doi:10.3390/nu9090995. | Study design
983 | Tittelbach, TJ, Mattes, RD, Gretebeck, RJ. Post-exercise substrate utilization after a high glucose vs. high fructose meal during negative energy balance in the obese. Obes Res. 2000. 8:496-505. doi:10.1038/oby.2000.62. | Intervention/exposure
984 | Toolsee, NA, Aruoma, OI, Gunness, TK, Kowlessur, S, Dambala, V, Murad, F, Googoolye, K, Daus, D, Indelicato, J, Rondeau, P, Bourdon, E, Bahorun, T. Effectiveness of green tea in a randomized human cohort: Relevance to diabetes and its complications. BioMed Research International. 2013. 2013. doi:10.1155/2013/412379. | Intervention/exposure
985 | Torres-Collado, L, Garcia-de la Hera, M, Navarrete-Munoz, EM, Compan-Gabucio, LM, Gonzalez-Palacios, S, Vioque, J. Coffee Drinking and Associated Factors in an Elderly Population in Spain. Int J Environ Res Public Health. 2018. 15. doi:10.3390/ijerph15081661. | Study design
986 | Toshihiro, M, Takanori, T, Junichi, N, Yoshinori, K, Hiroshi, S. The effect of oolong tea polymerized polyphenolsenriched beverage on body fat mass in obese human. Obesity facts.. 2013. 6:110. | Publication status
987 | Tovar, AR, Caamano Mdel, C, Garcia-Padilla, S, Garcia, OP, Duarte, MA, Rosado, JL. The inclusion of a partial meal replacement with or without inulin to a calorie restricted diet contributes to reach recommended intakes of micronutrients and decrease plasma triglycerides: a randomized clinical trial in obese Mexican women. Nutr J. 2012. 11:44. doi:10.1186/1475-2891-11-44. | Intervention/exposure
988 | Toxqui, L, Blanco-Rojo, R, Wright, I, Pérez-Granados, AM, Pilar Vaquero, M. Changes in blood pressure and lipid levels in young women consuming a vitamin D-fortified skimmed milk: A randomised controlled trial. Nutrients. 2013. 5:4966-4977. doi:10.3390/nu5124966. | Comparator; Outcome
989 | Treyzon, L, Chen, S, Hong, K, Yan, E, Carpenter, CL, Thames, G, Bowerman, S, Wang, HJ, Elashoff, R, Li, Z. A controlled trial of protein enrichment of meal replacements for weight reduction with retention of lean body mass. Nutr J. 2008. 7:23. doi:10.1186/1475-2891-7-23. | Health status
990 | Trier, C, Fonvig, CE, Bojsoe, C, Mollerup, PM, Gamborg, M, Pedersen, O, Hansen, T, Holm, JC. No influence of sugar, snacks and fast food intake on the degree of obesity or treatment effect in childhood obesity. Pediatr Obes. 2016. 11:506-512. doi:10.1111/ijpo.12094. | Health status
991 | Tripp, ML, Dahlberg, CJ, Eliason, S, Lamb, JJ, Ou, JJ, Gao, W, Bhandari, J, Graham, D, Dudleenamjil, E, Babish, JG. A Low-Glycemic, Mediterranean Diet and Lifestyle Modification Program with Targeted Nutraceuticals Reduces Body Weight, Improves Cardiometabolic Variables and Longevity Biomarkers in Overweight Subjects: A 13-Week Observational Trial. J Med Food. 2019. 22:479-489. doi:10.1089/jmf.2018.0063. | Study design; Intervention/exposure
992 | Tsai Ch, H, Chiu, WC, Yang, NC, Ouyang, CM, Yen, YH. A novel green tea meal replacement formula for weight loss among obese individuals: a randomized controlled clinical trial. Int J Food Sci Nutr. 2009. 60 Suppl 6:151-9. doi:10.1080/09637480903136667. | Intervention/exposure
993 | Tsitsimpikou, C, Tsarouhas, K, Kioukia-Fougia, N, Skondra, C, Fragkiadaki, P, Papalexis, P, Stamatopoulos, P, Kaplanis, I, Hayes, AW, Tsatsakis, A, Rentoukas, E. Dietary supplementation with tomato-juice in patients with metabolic syndrome: A suggestion to alleviate detrimental clinical factors. Food and Chemical Toxicology. 2014. 74:9-13. doi:10.1016/j.fct.2014.08.014. | Outcome
994 | Tsuchida, T, Minagawa, K, Mukai, K, Mizuno, Y, Mashiko, K. The comparative study of beta-cryptoxanthin derived from Satsuma mandarin for fat of human body. Japanese pharmacology and therapeutics. 2008. 36:247-253. | Language
995 | Tuomilehto, J, Hu, G, Bidel, S, Lindstrom, J, Jousilahti, P. Coffee consumption and risk of type 2 diabetes mellitus among middle-aged Finnish men and women. Jama. 2004. 291:1213-9. doi:10.1001/jama.291.10.1213. | Outcome
996 | Turel, O, Romashkin, A, Morrison, KM. A model linking video gaming, sleep quality, sweet drinks consumption and obesity among children and youth. Clin Obes. 2017. 7:191-198. doi:10.1111/cob.12191. | Study design
997 | Turner, L, Chaloupka, FJ. Encouraging trends in student access to competitive beverages in US public elementary schools, 2006-2007 to 2010-2011. Archives of Pediatrics and Adolescent Medicine. 2012. 166:673-675. doi:10.1001/archpediatrics.2012.487. | Study design; Intervention/exposure
998 | Uauy, R. Improving linear growth without excess body fat gain in women and children. Food Nutr Bull. 2013. 34:259-62. | Study design
999 | Udani, JK, Singh, BB, Barrett, ML, Singh, VJ. Evaluation of Mangosteen juice blend on biomarkers of inflammation in obese subjects: a pilot, dose finding study. Nutr J. 2009. 8:48. doi:10.1186/1475-2891-8-48. | Health status
1000 | Ueda, K, Sasai, H, Tsujimoto, T, Sanbongi, C, Ikegami, S, Kobayashi, H, Shioya, N, Suzuki, S, Nakata, Y. Randomized trial of amino acid mixture combined with physical activity promotion for abdominal fat reduction in overweight adults. Diabetes Metab Syndr Obes. 2018. 11:23-33. doi:10.2147/dmso.S153151. | Intervention/exposure
1001 | Uiterwaal, CS, Verschuren, WM, Bueno-de-Mesquita, HB, Ocke, M, Geleijnse, JM, Boshuizen, HC, Peeters, PH, Feskens, EJ, Grobbee, DE. Coffee intake and incidence of hypertension. Am J Clin Nutr. 2007. 85:718-23. doi:10.1093/ajcn/85.3.718. | Outcome
1002 | van der Gaag, EJ, Wieffer, R, van der Kraats, J. Advising Consumption of Green Vegetables, Beef, and Full-Fat Dairy Products Has No Adverse Effects on the Lipid Profiles in Children. Nutrients. 2017. 9. doi:10.3390/nu9050518. | Intervention/exposure
1003 | van der Horst, K, Oenema, A, van de Looij-Jansen, P, Brug, J. The ENDORSE study: research into environmental determinants of obesity related behaviors in Rotterdam schoolchildren. BMC Public Health. 2008. 8:142. doi:10.1186/1471-2458-8-142. | Study design
1004 | van der Sluis, ME, Lien, N, Twisk, JW, Steenhuis, IH, Bere, E, Klepp, KI, Wind, M. Longitudinal associations of energy balance-related behaviours and cross-sectional associations of clusters and body mass index in Norwegian adolescents. Public Health Nutr. 2010. 13:1716-21. doi:10.1017/s1368980010002272. | Intervention/exposure
1005 | van Dieren, S, Uiterwaal, CS, van der Schouw, YT, van der, Dl A, Boer, JM, Spijkerman, A, Grobbee, DE, Beulens, JW. Coffee and tea consumption and risk of type 2 diabetes. Diabetologia. 2009. 52:2561-9. doi:10.1007/s00125-009-1516-3. | Outcome
1006 | van Meijl, LE, Mensink, RP. Effects of low-fat dairy consumption on markers of low-grade systemic inflammation and endothelial function in overweight and obese subjects: an intervention study. Br J Nutr. 2010. 104:1523-7. doi:10.1017/s0007114510002515. | Intervention/exposure
1007 | van Meijl, LE, Mensink, RP. Low-fat dairy consumption reduces systolic blood pressure, but does not improve other metabolic risk parameters in overweight and obese subjects. Nutr Metab Cardiovasc Dis. 2011. 21:355-61. doi:10.1016/j.numecd.2009.10.008. | Intervention/exposure
1008 | van Nassau, F, Singh, AS, Cerin, E, Salmon, J, van Mechelen, W, Brug, J, Chinapaw, MJ. The Dutch Obesity Intervention in Teenagers (DOiT) cluster controlled implementation trial: intervention effects and mediators and moderators of adiposity and energy balance-related behaviours. Int J Behav Nutr Phys Act. 2014. 11:158. doi:10.1186/s12966-014-0158-0. | Study design; Intervention/exposure
1009 | van Woudenbergh, GJ, Kuijsten, A, Drogan, D, van der, ADL, Romaguera, D, Ardanaz, E, Amiano, P, Barricarte, A, Beulens, JWJ, Boeing, H, Bueno-de-Mesquita, HB, Dahm, CC, Chirlaque, MD, Clavel, F, Crowe, FL, Eomois, PP, Fagherazzi, G, Franks, PW, Halkjær, J, Khaw, KT, Masala, G, Mattiello, A, Nilsson, P, Overvad, K, Quirós, JR, Rolandsson, O, Romieu, I, Sacerdote, C, Sánchez, MJ, Schulze, MB, Slimani, N, Sluijs, I, Spijkerman, AMW, Tagliabue, G, Teucher, B, Tjønneland, A, Tumino, R, Forouhi, NG, Sharp, S, Langenberg, C, Feskens, EJM, Riboli, E, Wareham, NJ. Tea consumption and incidence of type 2 diabetes in Europe: The EPIC-interact case-cohort study. PLoS ONE. 2012. 7. doi:10.1371/journal.pone.0036910. | Outcome
1010 | Vanselow, MS, Pereira, MA, Neumark-Sztainer, D, Raatz, SK. Adolescent beverage habits and changes in weight over time: findings from Project EAT. Am J Clin Nutr. 2009. 90:1489-95. doi:10.3945/ajcn.2009.27573. | Study design
1011 | Vasilopoulou, D, Markey, O, Fagan, CC, Kliem, KE, Todd, S, Humphries, DJ, Jackson, KG, Givens, DI, Lovegrove, JA. A comparison of chronic consumption of dairy products varying in fatty acid composition on postprandial biomarkers of endothelial function: results from the RESET study. Proceedings of the nutrition society. 2017. 76. doi:10.1017/S002966511700324X. | Publication status
1012 | Vatanparast, H, Baxter-Jones, A, Faulkner, RA, Bailey, DA, Whiting, SJ. Positive effects of vegetable and fruit consumption and calcium intake on bone mineral accrual in boys during growth from childhood to adolescence: the University of Saskatchewan Pediatric Bone Mineral Accrual Study. Am J Clin Nutr. 2005. 82:700-6. doi:10.1093/ajcn.82.3.700. | Intervention/exposure; Outcome
1013 | Vazquez, C, Montagna, C, Alcaraz, F, Balsa, JA, Zamarron, I, Arrieta, F, Botella-Carretero, JI. Meal replacement with a low-calorie diet formula in weight loss maintenance after weight loss induction with diet alone. Eur J Clin Nutr. 2009. 63:1226-32. doi:10.1038/ejcn.2009.48. | Health status
1014 | Venkatakrishnan, K, Chiu, HF, Cheng, JC, Chang, YH, Lu, YY, Han, YC, Shen, YC, Tsai, KS, Wang, CK. Comparative studies on the hypolipidemic, antioxidant and hepatoprotective activities of catechin-enriched green and oolong tea in a double-blind clinical trial. Food Funct. 2018. 9:1205-1213. doi:10.1039/c7fo01449j. | Comparator
1015 | Venkatramanan, S, Joseph, SV, Chouinard, PY, Jacques, H, Farnworth, ER, Jones, PJ. Milk enriched with conjugated linoleic acid fails to alter blood lipids or body composition in moderately overweight, borderline hyperlipidemic individuals. J Am Coll Nutr. 2010. 29:152-9. | Intervention/exposure; Comparator
1016 | Ventura, AK, Loken, E, Birch, LL. Risk profiles for metabolic syndrome in a nonclinical sample of adolescent girls. Pediatrics. 2006. 118:2434-42. doi:10.1542/peds.2006-1527. | Intervention/exposure; Outcome
1017 | Ventura, E, Davis, J, Byrd-Williams, C, Alexander, K, McClain, A, Lane, CJ, Spruijt-Metz, D, Weigensberg, M, Goran, M. Reduction in risk factors for type 2 diabetes mellitus in response to a low-sugar, high-fiber dietary intervention in overweight Latino adolescents. Arch Pediatr Adolesc Med. 2009. 163:320-7. doi:10.1001/archpediatrics.2009.11. | Intervention/exposure
1018 | Verlaan, S, Bauer, JM, Sieber, C, Cederholm, T. Muscle mass, strength, and function effects of a high-whey, leucine-enriched nutritional intervention in sarcopenic elderly in a double blind, randomised controlled trial. European geriatric medicine. 2014. 5:S75-. | Publication status
1019 | Verlaan, S, Wijers, S, Bauer, J, Sieber, CC, Cederholm, T. A low caloric, leucine-enriched whey protein oral nutritional supplement affects body composition in sarcopenic older adults. European geriatric medicine. 2015. 6:S93. | Publication status
1020 | Verreijen, AM, De Wilde, J, Engberink, MF, Swinkels, S, Verlaan, S, Weijs, PJ. A high whey protein, leucine enriched supplement preserves muscle mass during intentional weight loss in obese older adults: a double blind randomized controlled trial. Clinical nutrition (edinburgh, scotland). 2013. 32:S3-. | Publication status
1021 | Verreijen, AM, Verlaan, S, Engberink, MF, Swinkels, S, de Vogel-van den Bosch, J, Weijs, PJ. A high whey protein-, leucine-, and vitamin D-enriched supplement preserves muscle mass during intentional weight loss in obese older adults: a double-blind randomized controlled trial. Am J Clin Nutr. 2015. 101:279-86. doi:10.3945/ajcn.114.090290. | Intervention/exposure
1022 | Vidal-Guevara, ML, Samper, M, Martínez-Silla, G, Canteras, M, Ros, G, Gil, A, Abellán, P. Meal replacement as a dietary therapy for weight control. Assessment in males and females with different degrees of obesity. Nutricion hospitalaria. 2004. 19:202-208. | Language
1023 | Vidya, TJ, Kulkarni, KS. Using herbal tea in the treatment modality: special reference to slirntea in overweight individuals. Anc Sci Life. 2002. 21:202-4. | Country
1024 | Vieira Senger, AE, Schwanke, CH, Gomes, I, Valle Gottlieb, MG. Effect of green tea (Camellia sinensis) consumption on the components of metabolic syndrome in elderly. J Nutr Health Aging. 2012. 16:738-42. doi:10.1007/s12603-012-0081-5. | Intervention/exposure
1025 | Vien, S, Luhovyy, BL, Patel, BP, Panahi, S, El Khoury, D, Mollard, RC, Hamilton, JK, Anderson, GH. Pre- and within-meal effects of fluid dairy products on appetite, food intake, glycemia, and regulatory hormones in children. Appl Physiol Nutr Metab. 2017. 42:302-310. doi:10.1139/apnm-2016-0251. | Outcome
1026 | Vigna, L, Galimberti, D, De Giuseppe, R, Cossovich, A, Sommaruga, D, De Liso, F, Gori, F, Ingenito, MR, Napolitano, F, Tomaino, L, Novembrino, C, Fenoglio, C, Bamonti, F. Natural vegan meal replacement: Metabolic and oxidative modulation on overweight subjects. Progress in Nutrition. 2017. 19:127-137. doi:10.23751/pn.v19i2.4774. | Intervention/exposure
1027 | Vijayalaxmi, BM, Shajahan, N, Patil, SL. Evaluation of the relationship between habitual consumption of coffee with reduced risk of diabetes. Research Journal of Pharmaceutical, Biological and Chemical Sciences. 2011. 2:396-401. | Outcome; Country
1028 | Villanueva, MG, He, J, Schroeder, ET. Periodized resistance training with and without supplementation improve body composition and performance in older men. Eur J Appl Physiol. 2014. 114:891-905. doi:10.1007/s00421-014-2821-1. | Intervention/exposure
1029 | Viner, RM, Cole, TJ. Who changes body mass between adolescence and adulthood? Factors predicting change in BMI between 16 year and 30 years in the 1970 British Birth Cohort. Int J Obes (Lond). 2006. 30:1368-74. doi:10.1038/sj.ijo.0803183. | Publication date
1030 | Vinson, JA, Burnham, BR, Nagendran, MV. Randomized, double-blind, placebo-controlled, linear dose, crossover study to evaluate the efficacy and safety of a green coffee bean extract in overweight subjects. Diabetes, Metabolic Syndrome and Obesity: Targets and Therapy. 2012. 5:21-27. | Publication status
1031 | Vogel, KA, Martin, BR, McCabe, LD, Peacock, M, Warden, SJ, McCabe, GP, Weaver, CM. The effect of dairy intake on bone mass and body composition in early pubertal girls and boys: a randomized controlled trial. Am J Clin Nutr. 2017. 105:1214-1229. doi:10.3945/ajcn.116.140418. | Intervention/exposure
1032 | Volek, JS, Gomez, AL, Scheett, TP, Sharman, MJ, French, DN, Rubin, MR, Ratamess, NA, McGuigan, MM, Kraemer, WJ. Increasing fluid milk favorably affects bone mineral density responses to resistance training in adolescent boys. J Am Diet Assoc. 2003. 103:1353-6. | Comparator
1033 | Volek, JS, Volk, BM, Gomez, AL, Kunces, LJ, Kupchak, BR, Freidenreich, DJ, Aristizabal, JC, Saenz, C, Dunn-Lewis, C, Ballard, KD, Quann, EE, Kawiecki, DL, Flanagan, SD, Comstock, BA, Fragala, MS, Earp, JE, Fernandez, ML, Bruno, RS, Ptolemy, AS, Kellogg, MD, Maresh, CM, Kraemer, WJ. Whey protein supplementation during resistance training augments lean body mass. J Am Coll Nutr. 2013. 32:122-35. doi:10.1080/07315724.2013.793580. | Intervention/exposure
1034 | Volger, S, Wadden, TA, Sarwer, DB, Moore, RH, Chittams, J, Diewald, LK, Panigrahi, E, Berkowitz, RI, Schmitz, K, Vetter, ML. Changes in eating, physical activity and related behaviors in a primary care-based weight loss intervention. Int J Obes (Lond). 2013. 37 Suppl 1:S12-8. doi:10.1038/ijo.2013.91. | Intervention/exposure; Health status
1035 | Vupadhyayula, PM, Gallagher, JC, Templin, T, Logsdon, SM, Smith, LM. Effects of soy protein isolate on bone mineral density and physical performance indices in postmenopausal women - A 2-year randomized, double-blind, placebo-controlled trial. Menopause. 2009. 16:320-328. doi:10.1097/gme.0b013e3181844893. | Outcome; Duplicate
1036 | Vupadhyayula, PM, Gallagher, JC, Templin, T, Logsdon, SM, Smith, LM. Effects of soy protein isolate on bone mineral density and physical performance indices in postmenopausal women--a 2-year randomized, double-blind, placebo-controlled trial. Menopause. 2009. 16:320-8. doi:10.1097/gme.0b013e3181844893. | Outcome
1037 | Wadden, TA, Volger, S, Sarwer, DB, Vetter, ML, Tsai, AG, Berkowitz, RI, Kumanyika, S, Schmitz, KH, Diewald, LK, Barg, R, Chittams, J, Moore, RH. A two-year randomized trial of obesity treatment in primary care practice. N Engl J Med. 2011. 365:1969-79. doi:10.1056/NEJMoa1109220. | Intervention/exposure; Health status
1038 | Wan Mohamed Radzi, CWJ, Salarzadeh Jenatabadi, H, Alanzi, ARA, Mokhtar, MI, Mamat, MZ, Abdullah, NA. Analysis of Obesity among Malaysian University Students: A Combination Study with the Application of Bayesian Structural Equation Modelling and Pearson Correlation. Int J Environ Res Public Health. 2019. 16. doi:10.3390/ijerph16030492. | Study design
1039 | Wang, H, Wen, Y, Du, Y, Yan, X, Guo, H, Rycroft, JA, Boon, N, Kovacs, EM, Mela, DJ. Effects of catechin enriched green tea on body composition. Obesity (Silver Spring). 2010. 18:773-9. doi:10.1038/oby.2009.256. | Country
1040 | Wang, SX, Wang, ZH, Cheng, XT, Li, J, Sang, ZP, Zhang, XD, Han, LL, Qiao, XY, Wu, ZM, Wang, ZH. Arsenic and fluoride expose in drinking water: Children’s IQ and growth in Shanyin Country, Shanxi Province, China. Environmental Health Perspectives. 2007. 115:643-647. doi:10.1289/ehp.9270. | Intervention/exposure; Country
1041 | Wang, SX, Wang, ZH, Cheng, XT, Li, J, Sang, ZP, Zhang, XD, Han, LL, Qiao, XY, Wu, ZM, Wang, ZQ. Arsenic and fluoride exposure in drinking water: children’s IQ and growth in Shanyin county, Shanxi province, China. Environ Health Perspect. 2007. 115:643-7. doi:10.1289/ehp.9270. | Study design; Country
1042 | Wang, T, Huang, T, Kang, JH, Zheng, Y, Jensen, MK, Wiggs, JL, Pasquale, LR, Fuchs, CS, Campos, H, Rimm, EB, Willett, WC, Hu, FB, Qi, L. Habitual coffee consumption and genetic predisposition to obesity: gene-diet interaction analyses in three US prospective studies. BMC Med. 2017. 15:97. doi:10.1186/s12916-017-0862-0. | Intervention/exposure
1043 | Warner, ML, Harley, K, Bradman, A, Vargas, G, Eskenazi, B. Soda consumption and overweight status of 2-year-old mexican-american children in california. Obesity (Silver Spring). 2006. 14:1966-74. doi:10.1038/oby.2006.230. | Study design
1044 | Wedick, NM, Brennan, AM, Sun, Q, Hu, FB, Mantzoros, CS, van Dam, RM. Effects of caffeinated and decaffeinated coffee on biological risk factors for type 2 diabetes: a randomized controlled trial. Nutr J. 2011. 10:93. doi:10.1186/1475-2891-10-93. | Intervention/exposure
1045 | Wedick, NM, Mantzoros, CS, Ding, EL, Brennan, AM, Rosner, B, Rimm, EB, Hu, FB, Van Dam, RM. The effects of caffeinated and decaffeinated coffee on sex hormone-binding globulin and endogenous sex hormone levels: a randomized controlled trial. Endocrine reviews. 2011. 32. | Outcome
1046 | Wegener, T, Melzig, MF, Görne, RC. Effect of pressed juice from artichoke flower buds on metabolic syndrome. Zeitschrift fur Phytotherapie. 2017. 38:206-211. doi:10.1055/s-0043-115774. | Language
1047 | Weiland, A, Bub, A, Barth, SW, Schrezenmeir, J, Pfeuffer, M. Effects of dietary milk- and soya-phospholipids on lipid-parameters and other risk indicators for cardiovascular diseases in overweight or obese men - two double-blind, randomised, controlled, clinical trials. J Nutr Sci. 2016. 5:e21. doi:10.1017/jns.2016.9. | Comparator
1048 | Weiland, A, Bub, A, Barth, SW, Schrezenmeir, J, Pfeuffer, M. Effects of dietary milk- and soya-phospholipids on lipid-parameters and other risk indicators for cardiovascular diseases in overweight or obese men – Two double-blind, randomised, controlled, clinical trials. Journal of Nutritional Science. 2016. 5. doi:10.1017/jns.2016.9. | Comparator
1049 | Weinheimer, EM, Conley, TB, Kobza, VM, Sands, LP, Lim, E, Janle, EM, Campbell, WW. Whey protein supplementation does not affect exercise training-induced changes in body composition and indices of metabolic syndrome in middle-aged overweight and obese adults. J Nutr. 2012. 142:1532-9. doi:10.3945/jn.111.153619. | Intervention/exposure
1050 | Weinheimer, EM, Conley, TB, Kobza, VM, Sands, LP, Lim, E, Janle, EM. Effects of whey protein supplements and exercise training on indices of metabolic syndrome in middle-aged overweight/obese adults. FASEB journal. 2011. 25. | Publication status
1051 | Weisgarber, KD, Candow, DG, Vogt, ES. Whey protein before and during resistance exercise has no effect on muscle mass and strength in untrained young adults. Int J Sport Nutr Exerc Metab. 2012. 22:463-9. | Intervention/exposure; Comparator
1052 | Wennersberg, MH, Smedman, A, Turpeinen, AM, Retterstol, K, Tengblad, S, Lipre, E, Aro, A, Mutanen, P, Seljeflot, I, Basu, S, Pedersen, JI, Mutanen, M, Vessby, B. Dairy products and metabolic effects in overweight men and women: results from a 6-mo intervention study. Am J Clin Nutr. 2009. 90:960-8. doi:10.3945/ajcn.2009.27664. | Intervention/exposure
1053 | Westerterp-Plantenga, MS, Lejeune, MP, Kovacs, EM. Body weight loss and weight maintenance in relation to habitual caffeine intake and green tea supplementation. Obes Res. 2005. 13:1195-204. doi:10.1038/oby.2005.142. | Intervention/exposure
1054 | Whittemore, R, Jeon, S, Grey, M. An internet obesity prevention program for adolescents. J Adolesc Health. 2013. 52:439-47. doi:10.1016/j.jadohealth.2012.07.014. | Intervention/exposure
1055 | Wiberger, M, Eiben, G, Lissner, L, Mehlig, K, Papoutsou, S, Hunsberger, M. Children consuming milk cereal drink are at increased risk for overweight: The IDEFICS Sweden study, on behalf of the IDEFICS Consortium. Scand J Public Health. 2014. 42:518-24. doi:10.1177/1403494814538124. | Population at Intervention/exposure
1056 | Wijga, AH, Scholtens, S, Bemelmans, WJ, Kerkhof, M, Koppelman, GH, Brunekreef, B, Smit, HA. Diet, Screen Time, Physical Activity, and Childhood Overweight in the General Population and in High Risk Subgroups: Prospective Analyses in the PIAMA Birth Cohort. J Obes. 2010. 2010. doi:10.1155/2010/423296. | Publication date; Language
1057 | Wilborn, CD, Outlaw, JJ, Mumford, PW, Urbina, SL, Hayward, S, Roberts, MD, Taylor, LW, Foster, CA. A Pilot Study Examining the Effects of 8-Week Whey Protein versus Whey Protein Plus Creatine Supplementation on Body Composition and Performance Variables in Resistance-Trained Women. Annals of Nutrition and Metabolism. 2017. 69:190-199. doi:10.1159/000452845. | Intervention/exposure; Comparator
1058 | Wilborn, CD, Outlaw, JJ, Mumford, PW, Urbina, SL, Hayward, S, Roberts, MD, Taylor, LW, Foster, CA. A Pilot Study Examining the Effects of 8-Week Whey Protein versus Whey Protein Plus Creatine Supplementation on Body Composition and Performance Variables in Resistance-Trained Women. Ann Nutr Metab. 2016. 69:190-199. doi:10.1159/000452845. | Comparator
1059 | Wilborn, CD, Taylor, LW, Outlaw, J, Williams, L, Campbell, B, Foster, CA, Smith-Ryan, A, Urbina, S, Hayward, S. The Effects of Pre- and Post-Exercise Whey vs. Casein Protein Consumption on Body Composition and Performance Measures in Collegiate Female Athletes. J Sports Sci Med. 2013. 12:74-9. | Intervention/exposure
1060 | Williams, CL, Strobino, BA, Brotanek, J. Weight control among obese adolescents: a pilot study. Int J Food Sci Nutr. 2007. 58:217-30. doi:10.1080/09637480701198083. | Intervention/exposure; Health status
1061 | Williams, RD, Jr, Housman, JM, Odum, M, Rivera, AE. Energy Drink Use Linked to High-sugar Beverage Intake and BMI among Teens. Am J Health Behav. 2017. 41:259-265. doi:10.5993/ajhb.41.3.5. | Study design
1062 | Wilsgaard, T, Jacobsen, BK, Arnesen, E. Determining lifestyle correlates of body mass index using multilevel analyses: the Tromso Study, 1979-2001. Am J Epidemiol. 2005. 162:1179-88. doi:10.1093/aje/kwi328. | Intervention/exposure
1063 | Wilsgaard, T, Jacobsen, BK, Arnesen, E. Determining lifestyle correlates of body mass index using multilevel analyses: The Tromsø study, 1979-2001. American Journal of Epidemiology. 2005. 162:1179-1188. doi:10.1093/aje/kwi328. | Duplicate
1064 | Wilson, KM, Kasperzyk, JL, Rider, JR, Kenfield, S, van Dam, RM, Stampfer, MJ, Giovannucci, E, Mucci, LA. Coffee consumption and prostate cancer risk and progression in the Health Professionals Follow-up Study. J Natl Cancer Inst. 2011. 103:876-84. doi:10.1093/jnci/djr151. | Outcome
1065 | Winterfeld, A. Starting healthy: preventing preschool obesity. NCSL Legisbrief. 2011. 19:1-2. | Study design
1066 | Witbracht, MG, Van Loan, M, Adams, SH, Keim, NL, Laugero, KD. Dairy food consumption and meal-induced cortisol response interacted to influence weight loss in overweight women undergoing a 12-week, meal-controlled, weight loss intervention. J Nutr. 2013. 143:46-52. doi:10.3945/jn.112.166355. | Intervention/exposure
1067 | Wojcicki, JM, Medrano, R, Lin, J, Epel, E. Increased Cellular Aging by 3 Years of Age in Latino, Preschool Children Who Consume More Sugar-Sweetened Beverages: A Pilot Study. Child Obes. 2018. 14:149-157. doi:10.1089/chi.2017.0159. | Outcome; Population at Intervention/exposure
1068 | Wojcicki, JM, Young, MB, Perham-Hester, KA, de Schweinitz, P, Gessner, BD. Risk factors for obesity at age 3 in Alaskan children, including the role of beverage consumption: results from Alaska PRAMS 2005-2006 and its three-year follow-up survey, CUBS, 2008-2009. PLoS One. 2015. 10:e0118711. doi:10.1371/journal.pone.0118711. | Study design
1069 | Wong, JMW, Ebbeling, CB, Robinson, L, Feldman, HA, Ludwig, DS. Effects of Advice to Drink 8 Cups of Water per Day in Adolescents With Overweight or Obesity: A Randomized Clinical Trial. JAMA Pediatr. 2017. 171:e170012. doi:10.1001/jamapediatrics.2017.0012. | Intervention/exposure
1070 | Wong, VCH, Maguire, JL, Omand, JA, Dai, DWH, Lebovic, G, Parkin, PC, O’Connor, DL, Birken, CS. A Positive Association Between Dietary Intake of Higher Cow’s Milk-Fat Percentage and Non-High-Density Lipoprotein Cholesterol in Young Children. J Pediatr. 2019. . doi:10.1016/j.jpeds.2019.03.047. | Outcome
1071 | Woo, J, Lau, W, Xu, L, Lam, CW, Zhao, X, Yu, W, Xing, X, Lau, E, Kuhn-Sherlock, B, Pocock, N, Eastell, R. Milk supplementation and bone health in young adult chinese women. J Womens Health (Larchmt). 2007. 16:692-702. doi:10.1089/jwh.2006.0222. | Outcome; Country
1072 | Worthy, SL, Lokken, K, Pilcher, K, Boeka, A. Demographic and lifestyle variables associated with obesity. Health Education Journal. 2010. 69:372-380. doi:10.1177/0017896910363330. | Study design; Health status
1073 | Wouters-Wesseling, W, Van Hooijdonk, C, Wagenaar, L, Bindels, J, de Groot, L, Van Staveren, W. The effect of a liquid nutrition supplement on body composition and physical functioning in elderly people. Clin Nutr. 2003. 22:371-7. | Intervention/exposure; Comparator
1074 | Wouters-Wesseling, W, Wouters, AE, Kleijer, CN, Bindels, JG, de Groot, CP, van Staveren, WA. Study of the effect of a liquid nutrition supplement on the nutritional status of psycho-geriatric nursing home patients. Eur J Clin Nutr. 2002. 56:245-51. doi:10.1038/sj.ejcn.1601319. | Intervention/exposure; Comparator
1075 | Wright, C, Zhou, J, Campbell, W. Increased milk protein isolate consumption during diet-induced energy restriction does not influence changes in bone quantity in overweight and obese older adults. Journal of bone and mineral research. 2017. 31. doi:10.1002/jbmr.3107. | Publication status
1076 | Wright, CS, McMorrow, AM, Weinheimer-Haus, EM, Campbell, WW. Whey Protein Supplementation and Higher Total Protein Intake Do Not Influence Bone Quantity in Overweight and Obese Adults Following a 36-Week Exercise and Diet Intervention. J Nutr. 2017. 147:179-186. doi:10.3945/jn.116.240473. | Intervention/exposure
1077 | Wright, LS, Rifas-Shiman, SL, Oken, E, Litonjua, AA, Gold, DR. Prenatal and Early Life Fructose, Fructose-Containing Beverages, and Midchildhood Asthma. Ann Am Thorac Soc. 2018. 15:217-224. doi:10.1513/AnnalsATS.201707-530OC. | Outcome
1078 | Wrotniak, BH, Georger, L, Hill, DL, Zemel, BS, Stettler, N. Association of dairy intake with weight change in adolescents undergoing obesity treatment. J Public Health (Oxf). 2018. . doi:10.1093/pubmed/fdy064. | Study design; Health status
1079 | Wuenstel, JW, Wadolowska, L, Slowinska, MA, Niedzwiedzka, E, Kowalkowska, J, Kurp, L. Intake of Dietary Fibre and Its Sources Related to Adolescents’ Age and Gender, but Not to Their Weight. Cent Eur J Public Health. 2016. 24:211-216. doi:10.21101/cejph.a4331. | Study design
1080 | Xanthopoulos, MS, Moore, RH, Wadden, TA, Bishop-Gilyard, CT, Gehrman, CA, Berkowitz, RI. The association between weight loss in caregivers and adolescents in a treatment trial of adolescents with obesity. J Pediatr Psychol. 2013. 38:766-74. doi:10.1093/jpepsy/jst024. | Intervention/exposure; Other (e.g., duplicative data)
1081 | Xu, DF, Sun, JQ, Chen, M, Chen, YQ, Xie, H, Sun, WJ, Lin, YF, Jiang, JJ, Sun, W, Chen, AF, Tang, QR. Effects of lifestyle intervention and meal replacement on glycaemic and body-weight control in Chinese subjects with impaired glucose regulation: a 1-year randomised controlled trial. Br J Nutr. 2013. 109:487-92. doi:10.1017/s0007114512001328. | Intervention/exposure
1082 | Xu, X, Pan, CL, Liu, GL, Chen, HM. Socioeconomic and lifestyle behavioral factors associated with overweight and obesity among rural to urban migrant children in central China. International Journal of Clinical and Experimental Medicine. 2016. 9:21635-21644. | Study design
1083 | Yamazaki, T, Kobayashi, Y, Manabe, F, Katayama, M, Taniguchi, Y, Kowatari, Y, Kondo, S. Body fat reducing effect of continuous consumption of the food containing matured hop extract - Randomized double-blind placebo-controlled parallel group study. Japanese pharmacology and therapeutics. 2016. 44:1193-1207. | Language
1084 | Yanagida, N, Minoura, T, Kitaoka, S. Does Terminating the Avoidance of Cow’s Milk Lead to Growth in Height. Int Arch Allergy Immunol. 2015. 168:56-60. doi:10.1159/000441499. | Intervention/exposure
1085 | Yang, H, Kim, H, Kim, JM, Chung, HW, Chang, N. Associations of dietary intake and metabolic syndrome risk parameters in Vietnamese female marriage immigrants in South Korea: The KoGES follow-up study. Nutr Res Pract. 2016. 10:313-20. doi:10.4162/nrp.2016.10.3.313. | Intervention/exposure; Outcome
1086 | Yang, HY, Yang, SC, Chao, JC, Chen, JR. Beneficial effects of catechin-rich green tea and inulin on the body composition of overweight adults. Br J Nutr. 2012. 107:749-54. doi:10.1017/s0007114511005095. | Comparator
1087 | Yang, LJ, Wu, GH, Yang, YL, Wu, YH, Zhang, L, Wang, MH, Mo, LY, Xue, G, Wang, CZ, Weng, XF. Nutrition, Physical Exercise, and the Prevalence of Sarcopenia in Elderly Residents in Nursing Homes in China. Med Sci Monit. 2019. 25:4390-4399. doi:10.12659/msm.914031. | Study design
1088 | Yannakoulia, M, Ntalla, I, Papoutsakis, C, Farmaki, AE, Dedoussis, GV. Consumption of vegetables, cooked meals, and eating dinner is negatively associated with overweight status in children. J Pediatr. 2010. 157:815-20. doi:10.1016/j.jpeds.2010.04.077. | Study design
1089 | Yannakoulia, M, Panagiotakos, D, Pitsavos, C, Skoumas, Y, Stafanadis, C. Eating patterns may mediate the association between marital status, body mass index, and blood cholesterol levels in apparently healthy men and women from the ATTICA study. Soc Sci Med. 2008. 66:2230-9. doi:10.1016/j.socscimed.2008.01.051. | Study design
1090 | Yeates, AJ, Gilmartin, N, O’Kane, SM, Pourshahidi, LK, Mulhern, MS, Strain, JJ. The effect of cow’s milk consumption on cardiometabolic health in women of childbearing age. Proceedings of the nutrition society. 2017. 76:E58-. doi:10.1017/S0029665117001318. | Publication status
1091 | Yen, YH. Supplement containing Camellia sinensis (green tea) may help treat obesity. Focus on alternative and complementary therapies. 2010. 15:15-16. doi:10.1211/fact.15.1.0006. | Study design; Publication status
1092 | Yin, J, Xue, HM, Chen, YY, Zhang, X, Quan, LM, Gong, YH, Cheng, G. Dietary energy density is positively associated with body composition of adults in Southwest China. Public Health Nutr. 2018. 21:1827-1834. doi:10.1017/s1368980018000277. | Study design
1093 | Yokomichi, H, Matsuoka, T, Ayuzawa, N, Suzuki, K, Sato, M, Shinohara, R, Mizorogi, S, Yamagata, Z. Daily sorghum tea reduces human body fat and plasma glucose - A clinical investigation of the efficacy and safety of long-term intake. Japanese Pharmacology and Therapeutics. 2015. 43:955-960. | Study design
1094 | Yoneda, T, Shoji, K, Takase, H, Hibi, M, Hase, T, Meguro, S, Tokimitsu, I, Kambe, H. Effectiveness and safety of 1-year ad libitum consumption of a high-catechin beverage under nutritional guidance. Metab Syndr Relat Disord. 2009. 7:349-56. doi:10.1089/met.2008.0061. | Comparator
1095 | Yoshimura, M, Maeda, A, Abe, K, Ohta, H, Kiso, Y, Takehara, I, Fukuhara, I, Sakane, N. Body fat reducing effect and safety of the beverage containing polyphenols derived from Japanese pagoda tree (enzymatically modified isoquercitrin) in overweight and obese subjects. Japanese pharmacology and therapeutics. 2008. 36:919-930. | Language
1096 | Yoshimura, M, Maeda, A, Nakamura, J, Kitagawa, Y, Shibata, H, Fukuhara, I. Body fat reducing effect of continuous consumption of the beverage containing quercetin glucosides (enzymatically modified isoquercitrin) in obese subjects. Japanese pharmacology and therapeutics. 2012. 40:901-914. | Language
1097 | Zahrou, FZ, Achour, A, El Menchawy, I, Benjed, K, Azlaf, M, El Hamdouchi, A, Elkari, K, Belghiti, H, Rjimati, EA, El Haloui, N, etal, . Impact of consumption of milk fortified in vitamins and minerals on the nutritional status of school children in Morocco. Acta physiologica. Conference: 1st congress of physiology and integrative biology, CPBI and 84th congress of french physiological society, SFP. France. 2015. 214:16. doi:10.1111/apha.12520. | Country
1098 | Zamani, M, Vahedi, A. Sugar-sweetened Beverages and Obesity: What Should Be Done on Health of Children and Adults?. Iran J Public Health. 2016. 45:964-5. | Study design; Publication status
1099 | Zhang, J. The impact of water quality on health: Evidence from the drinking water infrastructure program in rural China. Journal of Health Economics. 2012. 31:122-134. doi:10.1016/j.jhealeco.2011.08.008. | Intervention/exposure
1100 | Zhang, Q, Zhao, R, Gan, Q, Xu, P, Li, L, Pan, H, Li, S, Wang, T, Hu, X. The effect of two years milk and egg supplementation on body composition of pre-pubertal children in Chinese poor rural area. Annals of nutrition & metabolism. 2017. 71:888-. doi:10.1159/000480486. | Publication status
1101 | Zhang, T, Cai, L, Ma, L, Jing, J, Chen, Y, Ma, J. The prevalence of obesity and influence of early life and behavioral factors on obesity in Chinese children in Guangzhou. BMC Public Health. 2016. 16:954. doi:10.1186/s12889-016-3599-3. | Study design
1102 | Zhang, Y, Lee, ET, Cowan, LD, Fabsitz, RR, Howard, BV. Coffee consumption and the incidence of type 2 diabetes in men and women with normal glucose tolerance: the Strong Heart Study. Nutr Metab Cardiovasc Dis. 2011. 21:418-23. doi:10.1016/j.numecd.2009.10.020. | Outcome
1103 | Zhao, R, Pan, H, Gan, Q, Xu, P, Li, L, Hu, X, Lin, S, Wang, T, Zhang, Q. Changes in body composition of primary school students from Tianyang County, Guangxi Zhuang Autonomous Region after two years’ nutrition intervention. Wei sheng yan jiu [Journal of hygiene research]. 2018. 47:232-241. | Language
1104 | Zhou, J, Kim, JE, Campbell, W. Effects of milk protein concentrate on energy restriction-induced changes in body composition and indices of metabolic syndrome. FASEB journal. 2015. 29. | Publication status
1105 | Zhu, K, Devine, A, Suleska, A, Tan, CY, Toh, CZ, Kerr, D, Prince, RL. Adequacy and change in nutrient and food intakes with aging in a seven-year cohort study in elderly women. J Nutr Health Aging. 2010. 14:723-9. | Intervention/exposure; Outcome
1106 | Zhu, K, Greenfield, H, Zhang, Q, Du, X, Ma, G, Leng, HF, Cowell, CT, Fraser, DR. Growth and bone mineral accretion during puberty in Chinese girls: A five-year longitudinal study. Journal of Bone and Mineral Research. 2008. 23:167-172. doi:10.1359/jbmr.071006. | Country
1107 | Zhu, K, Kerr, DA, Meng, X, Devine, A, Solah, V, Binns, CW, Prince, RL. Two-Year Whey Protein Supplementation Did Not Enhance Muscle Mass and Physical Function in Well-Nourished Healthy Older Postmenopausal Women. J Nutr. 2015. 145:2520-6. doi:10.3945/jn.115.218297. | Comparator
1108 | Zhu, K, Zhang, Q, Foo, LH, Trube, A, Ma, G, Hu, X, Du, X, Cowell, CT, Fraser, DR, Greenfield, H. Growth, bone mass, and vitamin D status of Chinese adolescent girls 3 y after withdrawal of milk supplementation. Am J Clin Nutr. 2006. 83:714-21. doi:10.1093/ajcn.83.3.714. | Comparator; Country
1109 | Zilberter, T. Meal replacement and functional connectivity in the brain network for appetite: connecting the dots. Front Psychol. 2015. 6:547. doi:10.3389/fpsyg.2015.00547. | Study design
1110 | Zoellner, JM, You, W, Estabrooks, PA, Chen, Y, Davy, BM, Porter, KJ, Hedrick, VE, Bailey, A, Kruzliakova, N. Supporting maintenance of sugar-sweetened beverage reduction using automated versus live telephone support: findings from a randomized control trial. Int J Behav Nutr Phys Act. 2018. 15:97. doi:10.1186/s12966-018-0728-7. | Intervention/exposure; Comparator
1111 | Zuanazzi, C, Maccari, PA, Beninca, SC, Branco, CS, Theodoro, H, Vanderlinde, R, Siviero, J, Salvador, M. White grape juice increases high-density lipoprotein cholesterol levels and reduces body mass index and abdominal and waist circumference in women. Nutrition. 2019. 57:109-114. doi:10.1016/j.nut.2018.05.026. | Study design; Comparator

lxvi Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

lxvii This publication date range criteria was applied to the review of SSB evidence because the 2015 Dietary Guidelines Advisory Committee reviewed evidence on the relationship between added sugars, including SSB, and body weight/obesity, published up to January 2012.

lxviii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead ( The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups ).

lxix SSB: Sugar-sweetened beverage; LNCSB: Low and no-calroie sweetened beverage