# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
DPS: Division of Prevention Science
FNS: Food and Nutrition Service
GDM: Gestational diabetes mellitus
HBW: High birth weight
HHS: United States Department of Health and Human Services
IUGR: Intrauterine growth restriction
Kg/m^2^: Kilograms per meters squared
LBW: Low birth weight
LGA: Large for gestational age
LNCSB: Low- or no-calorie sweetened beverages
NESR: Nutrition Evidence Systematic Review
OASH: Office of the Assistant Secretary for Health
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
PCS: Prospective cohort study
RCT: Randomized controlled trial
SES: Socioeconomic status
SGA: Small for gestational age
SSB: Sugar-sweetened beverages
TEI: Total energy intake
USDA: United States Department of Agriculture