# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^vii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 2. Food, Beverage, and Nutrient Consumption During Pregnancy.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on beverage consumption during pregnancy and birth weight standardized for gestational age and sex. For this systematic review, the target population considered was women before and during pregnancy. The interventions or exposures considered were the type and amount of beverage consumption and the comparators were different amount of the same beverage (including no consumption and versions diluted with water), beverage vs. solid, beverage vs. water, sugar-sweetened beverages vs. no- or low-calorie sweetened beverages, and dairy milk with different amounts of fat. The outcomes considered were birth weight standardized for gestational age and sex and birth weight for length in infants at birth. The key confounders were child sex, maternal age, gestational age, race/ethnicity, socioeconomic status, anthropometry (pre-pregnancy BMI), pre-pregnancy beverage intake, smoking, and diagnosis of diabetes (gestational, type 1, type 2). The other factors to be considered were parity, total energy intake, timing, temporal use, sugar, protein, fiber, energy density, medications, and supplements.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

Table 5 provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 5 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials (including quasi experimental and controlled before-and-after studies); - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | Type and amount of beverage consumption—all beverage types will be considered; Example beverage categories include:; - Milk; - Flavored milk; - Dairy drinks & substitutes; - Juice; - Low- or no-calorie-sweetened beverages; - Sugar-sweetened beverages; - Nutritional beverages (e.g., protein shakes, smoothies, and meal replacements included if in a commercially available liquid form and labeled as a beverage, not a supplement); - Coffee and tea; - Plain water; - Flavored or enhanced water | - Studies focusing on specific nutrients added to beverages instead of a beverage as a whole (i.e., studies where beverages are the delivery mechanism for a nutrient); - Beverages that are not commercially available (e.g., experimentally manipulated beverages); - Supplements; - Alcohol (alone, not part of a beverage pattern)*; - Soups; - *Alcohol is being examined in a separate set of questions
Comparator | - Different amount of the same beverage (including no consumption and versions diluted with water); - Beverage vs. solid; - Beverage vs. water; - Sugar-sweetened beverages vs. low- or no-calorie sweetened beverages; - Dairy milk with different amounts of fat | - No comparator; - Studies comparing different types of beverages (with the exception of studies comparing a beverage to plain water, dairy milk with different amounts of fat, and sugar-sweetened beverages to low- or no-calorie sweetened beverages)
Outcomes | - Birth weight standardized for gestational age and sex (may be presented as SGA or LGA),; - Birth weight for Length for gestational age and sex | - Birth weight or birth weight for length not standardized for gestational age and sex
Temporality | - Studies when the exposure was assessed prior to the outcome | - Studies when the outcome was assessed prior to the exposure
Date of publication | - January 2000 – June 2019 | - Articles published prior to 2000
Publication status | - Articles published in peer-reviewed journals | - Articles that have not been peer reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, pre-prints, abstracts, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^viii^ | - Studies conducted in Very High or High Human Development Countries | - Studies conducted in Medium or lower Human Development Countries
Study participants | - Human participants; - Females who are pregnant; - Females capable of becoming pregnant; - Neonates | - Animal and in vitro models; - Hospitalized patients, when hospitalization is not related to pregnancy, birth and immediate postpartum; - Pregnancies conceived ONLY using Assisted Reproductive Technologies; - Studies that exclusively enroll multiple gestation pregnancies; - Studies that enroll both singleton and multiple pregnancies and do not account for singleton and multiple gestation in the design or analyses and only present aggregate findings
Health status of study participants | - Studies that enroll mothers who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some mothers diagnosed with a disease; - Studies that enroll mothers with infants born full-term (≥37 and 0/7 weeks gestational age); - Studies that enroll some mothers with infants who are born preterm (gestational age <37 and 0/7 weeks), with low birth weight (2500g), and/or small for gestational age | - Studies that exclusively enroll preterm infants (gestational age <37 and 0/7 weeks); - Studies that exclusively enroll mothers diagnosed with a disease, or hospitalized with an illness or injury (For this criterion, studies that exclusively enroll mothers with obesity will not be excluded)

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) searched: June 10, 2019
- Date range searched: January 1, 2000-June 10, 2019
- Search Terms:
  - #1 - “Beverages”[Mesh:noexp] OR beverage[tiab] OR beverages[tiab] OR sports drink* OR protein drink* OR fortified drink* OR sweetened drink* OR sweet drink* OR sugary drink* OR dairy drink* OR chocolate drink* OR nutritional drink* OR smoothie*[tiab] OR protein shake* OR meal replacement*[tiab] OR carbonated drink*[tiab] OR soft drink*[tiab] OR soda[tiab] OR sodas[tiab] OR caffeinated drink*[tiab] OR “Drinking Water”[Mesh] OR drinking water[tiab] OR bottled water[tiab] OR “Carbonated Beverages”[Mesh] OR carbonated water[tiab] OR sparkling water[tiab] OR flavored water[tiab] OR flavoured water[tiab] OR flavoured drink[tiab] OR flavored drink* OR “Energy Drinks”[Mesh] OR energy drink*[tiab] OR sugar sweetened drink* OR “Fruit and Vegetable Juices”[Mesh] OR juice[tiab] OR juices[tiab] OR fruit drink* OR fizzy drink* OR “Coffee”[Mesh] OR coffee[tiab] OR “Tea”[Mesh] OR tea[tiab] OR “Milk”[Mesh:noexp] OR milk[tiab] OR “Soy Milk”[Mesh] OR soymilk[tiab] OR “Buttermilk”[Mesh] OR buttermilk[tiab] OR “Whey”[Mesh] OR whey[tiab] OR liquid[tiab] OR liquids[tiab]
  - #2 - “Pregnancy”[Mesh] OR “Pregnancy Complications”[Mesh] OR “Prenatal Exposure Delayed Effects”[Mesh] OR “Maternal Exposure”[Mesh] OR “Pregnant Women”[Mesh] OR pregnan*[tiab] OR pre-pregnancy[tiab] OR prenatal[tiab] OR antenatal[tiab] OR maternal[tiab] OR “Mothers”[Mesh] OR mother[tiab] OR mothers[tiab] OR postpartum[tiab] OR perinatal[tiab] OR peri-natal[tiab] OR pre-conception[tiab] OR preconception[tiab] OR peri-conception[tiab] OR periconception[tiab] OR “Peripartum Period”[Mesh] OR peripartum[tiab] OR peri-partum[tiab] OR gestation*[tiab] OR natal[tiab] OR puerperium[tiab] OR “Maternal Nutritional Physiological Phenomena”[Mesh]
  - #3 - “Birth Weight”[Mesh] OR birth weight*[tiab] OR “Infant, Low Birth Weight”[Mesh] OR body weight[tiab] OR healthy weight[tiab] OR “weight gain”[tiab] OR “weight loss”[tiab] OR “Overweight”[Mesh] OR overweight[tiab] OR obesity[tiab] OR “Thinness”[Mesh] OR underweight[tiab] OR under weight[tiab] OR “Fetal Weight”[Mesh] OR fetal weight* OR “Waist Circumference”[Mesh] OR waist circumference[tiab] OR “body size”[tiab] OR “Fetal Growth Retardation”[Mesh] OR fetal growth[tiab] OR IUGR[tiab] OR “Intrauterine growth restriction” OR “intrauterine growth restriction” OR “Fetal Development”[Mesh:noexp] OR fetal development[tiab] OR “Umbilical Arteries”[Mesh] OR umbilical arter*[tiab] OR “Uterine Artery”[Mesh] OR uterine arter*[tiab] OR “Waist-Height Ratio”[Mesh] OR waist height ratio[tiab] OR “Body Mass Index”[Mesh] OR body mass index[tiab] OR BMI[tiab] OR z-score[tiab] OR “Adiposity”[Mesh] OR adiposity[tiab] OR “body fat”[tiab]
  - #4 - (#1 AND #2 AND #3) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2014/01/01 to 2019/06/10; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: June 10, 2019
- Date range searched: January 1, 2000-June 10, 2019
- Search Terms:
  - #1 - [mh ^Beverages] OR [mh “Drinking Water”] OR [mh “Carbonated Beverage”] OR [mh “Energy Drink”] OR [mh “Fruit and Vegetable Juice”] OR [mh Coffee] OR [mh ^Milk]”
  - #2 - (beverage OR beverages OR “sports drink” OR “protein drink” OR “fortified drink” OR “sweetened drink” OR “sweet drink” OR “sugary drink” OR “dairy drink” OR “chocolate drink” OR “nutritional drink” OR smoothie* OR “protein shake” OR “meal replacement” OR “carbonated drink” OR “soft drink” OR soda OR sodas OR “caffeinated drink” OR “drinking water” OR “bottled water” OR “carbonated water” OR “sparkling water” OR “flavored water” OR “flavoured water” OR “flavoured drink” OR “flavored drink*” OR “energy drink” OR “sugar sweetened drink” OR juice OR juices OR “fruit drink” OR “fizzy drink” OR coffee OR tea OR milk OR soymilk OR buttermilk OR whey OR liquid OR liquids):ti,ab,kw”
  - #3 - #1 OR #2
  - #4 - [mh “Pregnancy”] OR [mh “Pregnancy Complications”] OR [mh “Prenatal Exposure Delayed Effects”] OR [mh “Maternal Exposure”] OR [mh “Pregnant Women”] OR [mh “Mothers”] OR [mh “Peripartum Period”] OR [mh “Maternal Nutritional Physiological Phenomena”]
  - #5 - (pregnancy OR “pre-pregnancy” OR prenatal OR antenatal OR maternal OR mother OR mothers OR postpartum OR perinatal OR peri-natal OR pre-conception OR preconception OR peri-conception OR periconception OR peripartum OR peri-partum OR gestation OR natal OR puerperium):ti,ab,kw
  - #6 - #4 OR #5
  - #7 - [mh “Birth Weight”] OR [mh “Infant, Low Birth Weight”] OR [mh “Overweight”] OR [mh “Thinness”] OR [mh “Fetal Weight”] OR [mh “Waist Circumference”] OR [mh “Fetal Growth Retardation”] OR [mh ^“Fetal Development”] OR [mh “Umbilical Arteries”] OR [mh “Uterine Artery”] OR [mh “Waist-Height Ratio”] OR [mh “Body Mass Index”] OR [mh “Adiposity”]
  - #8 - (“birth weight” OR “body weight” OR “healthy weight” OR “weight gain” OR “weight loss” OR overweight OR obesity OR underweight OR “under weight” OR “fetal weight” OR “waist circumference” OR “body size” OR “fetal growth” OR IUGR OR “Intrauterine growth restriction” OR “intrauterine growth restriction” OR “fetal development” OR “umbilical arter” OR “uterine artery” OR “waist height ratio” OR “body mass index” OR BMI OR z-score OR adiposity OR “body fat”):ti,ab,kw
  - #9 - #7 OR #8
  - #10 - #3 AND #6 AND #9” with Publication Year from 2000 to 2019, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) searched: June 10, 2019
- Date range searched: January 1, 2000-June 10, 2019
- Search Terms:
  - #1 - ‘beverage’/mj OR ‘drinking water’/mj OR ‘carbonated beverage’/de OR ‘energy drink’/de OR ‘fruit and vegetable juice’/exp/mj OR ‘coffee’/exp/mj OR ‘milk’/mj OR ‘soybean milk’/de OR ‘buttermilk’/de OR ‘whey’/de
  - #2 - beverage:ab,ti OR beverages:ab,ti OR ‘sports drink*’:ab,ti OR ‘protein drink*’:ab,ti OR ‘fortified drink*’:ab,ti OR ‘sweetened drink*’:ab,ti OR ‘sweet drink*’:ab,ti OR ‘sugary drink*’:ab,ti OR ‘dairy drink*’:ab,ti OR ‘chocolate drink*’:ab,ti OR ‘nutritional drink*’:ab,ti OR smoothie*:ab,ti OR ‘protein shake*’:ab,ti OR ‘meal replacement*’:ab,ti OR ‘carbonated drink*’:ab,ti OR ‘soft drink*’:ab,ti OR soda:ab,ti OR sodas:ab,ti OR ‘caffeinated drink*’:ab,ti OR ‘drinking water’:ab,ti OR ‘bottled water’:ab,ti OR ‘carbonated water’:ab,ti OR ‘sparkling water’:ab,ti OR ‘flavored water’:ab,ti OR ‘flavoured water’:ab,ti OR ‘flavoured drink’:ab,ti OR ‘flavored drink*’:ab,ti OR ‘energy drink*’:ab,ti OR ‘sugar sweetened drink*’:ab,ti OR juice:ab,ti OR juices:ab,ti OR ‘fruit drink*’:ab,ti OR ‘fizzy drink*’:ab,ti OR coffee:ab,ti OR tea:ab,ti OR milk:ab,ti OR soymilk:ab,ti OR buttermilk:ab,ti OR whey:ab,ti OR liquid:ab,ti OR liquids:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘pregnancy’/exp/mj OR ‘pregnancy complication’/exp/mj OR ‘prenatal exposure’/mj OR ‘maternal exposure’/mj OR ‘pregnant woman’/mj OR ‘mother’/mj OR ‘puerperium’/mj OR ‘maternal nutrition’/mj
  - #5 - pregnan*:ab,ti OR ‘pre pregnancy’:ab,ti OR prenatal:ab,ti OR antenatal:ab,ti OR maternal:ab,ti OR mother:ab,ti OR mothers:ab,ti OR postpartum:ab,ti OR perinatal:ab,ti OR ‘peri natal’:ab,ti OR ‘pre conception’:ab,ti OR preconception:ab,ti OR ‘peri conception’:ab,ti OR periconception:ab,ti OR peripartum:ab,ti OR ‘peri partum’:ab,ti OR gestation*:ab,ti OR natal:ab,ti OR puerperium:ab,ti
  - #6 - #4 OR #5
  - #7 - ‘birth weight’/exp/mj OR ‘obesity’/exp/mj OR ‘underweight’/de OR ‘fetus weight’/de OR ‘waist circumference’/de OR ‘intrauterine growth retardation’ OR ‘fetus development’/exp OR ‘umbilical artery’ OR ‘uterine artery’ OR ‘waist to height ratio’ OR ‘body mass index z score’ OR ‘body fat’
  - #8 - ‘birth weight*’:ab,ti OR ‘body weight’:ab,ti OR ‘healthy weight’:ab,ti OR ‘weight gain’:ab,ti OR ‘weight loss’:ab,ti OR overweight:ab,ti OR obesity:ab,ti OR underweight:ab,ti OR ‘under weight’:ab,ti OR ‘fetal weight’:ab,ti OR ‘waist circumference’:ab,ti OR ‘body size’:ab,ti OR ‘fetal growth’:ab,ti OR iugr:ab,ti OR ‘intrauterine growth restriction’:ab,ti OR ‘fetal development’:ab,ti OR ‘umbilical arter*’:ab,ti OR ‘uterine arter*’:ab,ti OR ‘waist height ratio’:ab,ti OR ‘body mass index’:ab,ti OR bmi:ab,ti OR ‘z-score’:ab,ti OR adiposity:ab,ti OR ‘body fat’:ab,ti
  - #9 - #7 OR #8
  - #10 - #3 AND #6 AND #9
  - #11 - #3 AND #6 AND #9 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2019]/py

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: June 10, 2019
- Date range searched: January 1, 2000-June 10, 2019
- Search Terms:
  - #S1 - (MH “Beverages+” OR MH “Water Supply”)
  - #S2 - (beverage OR beverages OR “sports drink*” OR “protein drink*” OR “fortified drink*” OR “sweetened drink*” OR “sweet drink*” OR “sugar drink*” OR “sugary drink*” OR “dairy drink*” OR “chocolate drink*” OR “nutritional drink*” OR smoothie* OR “protein shake*” OR “meal replacement*” OR “carbonated drink*” OR “soft drink*” OR soda OR sodas OR “caffeinated drink*” OR “drinking water” OR “bottled water*” OR “carbonated water*” OR “sparkling water*” OR “flavored water*” OR “flavoured water*” OR “flavoured drink*” OR “flavored drink*” OR “energy drink*” OR “sugar sweetened drink*” OR juice OR juices OR “fruit drink*” OR “fizzy drink*” OR coffee OR tea OR milk OR soymilk OR buttermilk OR whey OR liquid*)
  - #S3 - S1 OR S2
  - #S4 - (MH “Pregnancy+” OR MH “Pregnancy Complications+” OR MH “Prenatal Exposure Delayed Effects” OR MH “Maternal Exposure” OR MH “Expectant Mothers” OR MH “Mothers” OR MH “Puerperium” OR MH “Maternal Nutritional Physiology”)
  - #S5 - (pregnan* OR “pre pregnancy” OR prenatal OR antenatal OR maternal OR mother OR mothers OR postpartum OR perinatal OR “peri natal” OR “pre conception” OR preconception OR “peri conception” OR periconception OR peripartum OR “peri partum” OR gestation* OR natal OR puerperium)
  - #S6 - S4 OR S5
  - #S7 - (MH “Birth Weight” OR MH “Infant, Low Birth Weight” OR MH “Fetal Weight” OR MH “Obesity” OR MH “Thinness” OR MH “Fetal Growth Retardation” OR MH “Fetal Development” OR MH “Umbilical Arteries” OR MH “Waist Circumference” OR MH “Waist-Hip Ratio” OR MH “Body Mass Index” OR MH “Adipose Tissue”)
  - #S8 - (‘birth weight’/exp OR ‘obesity’/exp OR ‘underweight’ OR ‘fetus weight’ OR ‘waist circumference’ OR ‘intrauterine growth retardation’ OR ‘fetus development’/exp OR ‘umbilical artery’ OR ‘waist to height ratio’ OR ‘body mass index z score’ OR ‘body fat’)
  - #S9 - S7 OR S8
  - #S10 - S3 AND S6 AND S9
  - #S11 - ( S3 AND S6 AND S9 ) NOT ( MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication )

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 6 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between beverage consumption during pregnancy and birth weight. The literature search yielded 4,447 articles. During title screening, 3,901 articles were screened out. During abstract screening, 377 articles were screened out. During full-text screening, 150 articles were screened out. During the hand search, 0 additional articles were identified to include. A total of 19 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes columns for the categories of inclusion and exclusion criteria (see Table 5) that studies were excluded based on. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 6 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | Abouk, R, Adams, S. Birth outcomes in Flint in the early stages of the water crisis. J Public Health Policy. 2018. 39(1):68-85. doi:10.1057/s41271-017-0097-5. | Intervention/Exposure
2 | Abraham, A, Mathews, JE, Sebastian, A, Chacko, KP, Sam, D. A nested case-control study to evaluate the association between fetal growth restriction and vitamin B12 deficiency. Aust N Z J Obstet Gynaecol. 2013. 53(4):399-402. doi:10.1111/ajo.12057. | Intervention/Exposure
3 | Aggazzotti, G, Righi, E, Fantuzzi, G, Biasotti, B, Ravera, G, Kanitz, S, Barbone, F, Sansebastiano, G, Battaglia, MA, Leoni, V, Fabiani, L, Triassi, M, Sciacca, S. Chlorination by-products (CBPs) in drinking water and adverse pregnancy outcomes in Italy. J Water Health. 2004. 2(4):233-47. | Study design; Intervention/Exposure
4 | Aghaei, M, Derakhshani, R, Raoof, M, Dehghani, M, Mahvi, AH. Effect of fluoride in drinking water on birth height and weight: An ecological study in Kerman Province, Zarand county, Iran. Fluoride. 2015. 48(2):160-168. | Intervention/Exposure
5 | Almberg, KS, Turyk, ME, Jones, RM, Rankin, K, Freels, S, Graber, JM, Stayner, LT. Arsenic in drinking water and adverse birth outcomes in Ohio. Environ Res. 2017. 157:52-59. doi:10.1016/j.envres.2017.05.010. | Intervention/Exposure
6 | Almberg, KS, Turyk, ME, Jones, RM, Rankin, K, Freels, S, Stayner, LT. Atrazine contamination of drinking water and adverse birth outcomes in community water systems with elevated atrazine in Ohio, 2006–2008. International Journal of Environmental Research and Public Health. 2018. 15(9). doi:10.3390/ijerph15091889. | Intervention/Exposure
7 | Alomar, MJ. Evaluation of caffeine consumption and effect during pregnancy among women in the UAE. International Journal of Pharmacy and Pharmaceutical Sciences. 2016. 8(6):101-103. | Study design; Intervention/Exposure
8 | Anjum, N, Naveen, A, Sheikh, S. Role of nutrition in pregnancy and its effect on fetal birth weight. Pakistan Journal of Medical and Health Sciences. 2013. 7(2). | Country
9 | Aschengrau, A, Weinberg, J, Rogers, S, Gallagher, L, Winter, M, Vieira, V, Webster, T, Ozonoff, D. Prenatal exposure to tetrachloroethylene-contaminated drinking water and the risk of adverse birth outcomes. Environ Health Perspect. 2008. 116(6):814-20. doi:10.1289/ehp.10414. | Intervention/Exposure
10 | Aschengrau, A, Weinberg, J, Rogers, S, Gallagher, L, Winter, M, Vieira, V, Webster, T, Ozonoff, D. Prenatal exposure to tetrachloroethylene-contamination drinking water and the risk of adverse birth outcomes. Environmental Health Perspectives. 2008. 116(6):814-820. doi:10.1289/ehp.10414. | Intervention/Exposure; Duplicate
11 | Backstrand, JR, Allen, LH, Martinez, E, Pelto, GH. Maternal consumption of pulque, a traditional central Mexican alcoholic beverage: Relationships to infant growth and development. Public Health Nutrition. 2001. 4(4):883-891. | Intervention/Exposure
12 | Bada, HS, Das, A, Bauer, CR, Shankaran, S, Lester, BM, Gard, CC, Wright, LL, LaGasse, L, Higgins, R. Low birth weight and preterm births: etiologic fraction attributable to prenatal drug exposure. Journal of Perinatology. 2005. 25(10):631-637. | Intervention/Exposure
13 | Bakker, R, Steegers, EA, Obradov, A, Raat, H, Hofman, A, Jaddoe, VW. Maternal caffeine intake from coffee and tea, fetal growth, and the risks of adverse birth outcomes: the Generation R Study. Am J Clin Nutr. 2010. 91(6):1691-8. doi:10.3945/ajcn.2009.28792. | Intervention/Exposure
14 | Balat, O, Balat, A, Ugur, MG, Pence, S. The effect of smoking and caffeine on the fetus and placenta in pregnancy. Clin Exp Obstet Gynecol. 2003. 30(1):57-9. | Study design; Intervention/Exposure
15 | Bech, BH, Obel, C, Henriksen, TB, Olsen, J. Effect of reducing caffeine intake on birth weight and length of gestation: randomised controlled trial. Bmj. 2007. 334(7590):409. doi:10.1136/bmj.39062.520648.BE. | Other
16 | Bertelsen, RJ, Brantsaeter, AL, Magnus, MC, Haugen, M, Myhre, R, Jacobsson, B, Longnecker, MP, Meltzer, HM, London, SJ. Probiotic milk consumption in pregnancy and infancy and subsequent childhood allergic diseases. J Allergy Clin Immunol. 2014. 133(1):165-71.e1-8. doi:10.1016/j.jaci.2013.07.032. | Outcome
17 | Bloom, MS, Neamtiu, IA, Surdu, S, Pop, C, Anastasiu, D, Appleton, AA, Fitzgerald, EF, Gurzau, ES. Low level arsenic contaminated water consumption and birth outcomes in Romania-An exploratory study. Reprod Toxicol. 2016. 59:8-16. doi:10.1016/j.reprotox.2015.10.012. | Intervention/Exposure
18 | Bonou, SG, Levallois, P, Giguere, Y, Rodriguez, M, Bureau, A. Prenatal exposure to drinking-water chlorination by-products, cytochrome P450 gene polymorphisms and small-for-gestational-age neonates. Reprod Toxicol. 2017. 73:75-86. doi:10.1016/j.reprotox.2017.07.019. | Study design; Intervention/Exposure
19 | Bracken, MB, Triche, EW, Belanger, K, Hellenbrand, K, Leaderer, BP. Association of maternal caffeine consumption with decrements in fetal growth. Am J Epidemiol. 2003. 157(5):456-66. doi:10.1093/aje/kwf220. | Other
20 | Brantsæter, AL, Haugen, M, Myhre, R, Sengpiel, V, Englund-Ögge, L, Nilsen, RM, Borgen, I, Duarte-Salles, T, Papadopoulou, E, Vejrup, K, Von Ruesten, A, Hillesund, ER, Birgisdottir, BE, Magnus, P, Trogstad, L, Jacobsson, B, Bacelis, J, Myking, S, Knutsen, HK, Kvalem, HE, Alexander, J, Mendez, M, Meltzer, HM. Diet matters, particularly in pregnancy – Results from MoBa studies of maternal diet and pregnancy outcomes. Norsk Epidemiologi. 2014. 24(1-2):63-77. | Study design
21 | Bukowski, J, Somers, G, Bryanton, J. Agricultural contamination of groundwater as a possible risk factor for growth restriction or prematurity. J Occup Environ Med. 2001. 43(4):377-83. | Study design; Intervention/Exposure
22 | Cao, WC, Zeng, Q, Luo, Y, Chen, HX, Miao, DY, Li, L, Cheng, YH, Li, M, Wang, F, You, L, Wang, YX, Yang, P, Lu, WQ. Blood Biomarkers of Late Pregnancy Exposure to Trihalomethanes in Drinking Water and Fetal Growth Measures and Gestational Age in a Chinese Cohort. Environ Health Perspect. 2016. 124(4):536-41. doi:10.1289/ehp.1409234. | Study design
23 | Chan, GM, McElligott, K, McNaught, T, Gill, G. Effects of dietary calcium intervention on adolescent mothers and newborns: A randomized controlled trial. Obstet Gynecol. 2006. 108(3 Pt 1):565-71. doi:10.1097/01.AOG.0000231721.42823.9e. | Intervention/Exposure
24 | Chen, LW, Murrin, CM, Mehegan, J, Kelleher, CC, Phillips, CM. Maternal, but not paternal or grandparental, caffeine intake is associated with childhood obesity and adiposity: The Lifeways Cross-Generation Cohort Study. Am J Clin Nutr. 2019. 109(6):1648-1655. doi:10.1093/ajcn/nqz019. | Outcome; Population
25 | Chiaffarino, F, Parazzini, F, Chatenoud, L, Ricci, E, Tozzi, L, Chiantera, V, Maffioletti, C, Fedele, L. Coffee drinking and risk of preterm birth. Eur J Clin Nutr. 2006. 60(5):610-3. doi:10.1038/sj.ejcn.1602358. | Study design
26 | Clark, DC. Association of Dairy Protein Intake During Pregnancy with Birth Weight. Food Nutr Bull. 2018. 39(2_suppl):S54-s59. doi:10.1177/0379572118775824. | Study design
27 | Coelho Nde, L, Cunha, DB, Esteves, AP, Lacerda, EM, Theme Filha, MM. Dietary patterns in pregnancy and birth weight. Rev Saude Publica. 2015. 49:62. doi:10.1590/s0034-8910.2015049005403. | Intervention/Exposure
28 | Conde, A, Teves, C, Figueiredo, B. Maternal coffee intake and associated risk factors: effects on fetal growth and activity. Acta Med Port. 2011. 24(2):241-8. | Outcome
29 | Costet, N, Garlantezec, R, Monfort, C, Rouget, F, Gagniere, B, Chevrier, C, Cordier, S. Environmental and urinary markers of prenatal exposure to drinking water disinfection by-products, fetal growth, and duration of gestation in the PELAGIE birth cohort (Brittany, France, 2002-2006). Am J Epidemiol. 2012. 175(4):263-75. doi:10.1093/aje/kwr419. | Intervention/Exposure
30 | Costet, Nathalie, Garlantézec, Ronan, Monfort, Christine, Rouget, Florence, Gagnière, Bertrand, Chevrier, Cécile, Cordier, Sylvaine. Environmental and Urinary Markers of Prenatal Exposure to Drinking Water Disinfection By-Products, Fetal Growth, and Duration of Gestation in the PELAGIE Birth Cohort (Brittany, France, 2002–2006). American Journal of Epidemiology. 2012. 175(4):263-275. | Intervention/Exposure; Duplicate
31 | Cuco, G, Fernandez-Ballart, J, Sala, J, Viladrich, C, Iranzo, R, Vila, J, Arija, V. Dietary patterns and associated lifestyles in preconception, pregnancy and postpartum. Eur J Clin Nutr. 2006. 60(3):364-71. doi:10.1038/sj.ejcn.1602324. | Intervention/Exposure; Outcome
32 | Currie, J, Zivin, JG, Meckel, K, Neidell, M, Schlenker, W. Something in the water: contaminated drinking water and infant health. Can J Econ. 2013. 46(3):791-810. doi:10.1111/caje.12039. | Intervention/Exposure
33 | Danileviciute, A, Grazuleviciene, R, Vencloviene, J, Paulauskas, A, Nieuwenhuijsen, MJ. Exposure to drinking water trihalomethanes and their association with low birth weight and small for gestational age in genetically susceptible women. Int J Environ Res Public Health. 2012. 9(12):4470-85. doi:10.3390/ijerph9124470. | Intervention/Exposure
34 | Dharmalingam, A, Navaneetham, K, Krishnakumar, CS. Nutritional status of mothers and low birth weight in India. Matern Child Health J. 2010. 14(2):290-8. doi:10.1007/s10995-009-0451-8. | Country
35 | Diet & nutrition. Good news: caffeine in pregnancy doesn’t affect the baby’s growth…and folic acid seems to prevent cleft lip. Child Health Alert. 2007. 25:5-6. | Publication status
36 | Donazar-Ezcurra, M, Lopez-Del Burgo, C, Martinez-Gonzalez, MA, Basterra-Gortari, FJ, de Irala, J, Bes-Rastrollo, M. Soft drink consumption and gestational diabetes risk in the SUN project. Clin Nutr. 2018. 37(2):638-645. doi:10.1016/j.clnu.2017.02.005. | Outcome
37 | Ehrlich, SF, Rosas, LG, Ferrara, A, King, JC, Abrams, B, Harley, KG, Hedderson, MM, Eskenazi, B. Pregnancy glucose levels in women without diabetes or gestational diabetes and childhood cardiometabolic risk at 7 years of age. J Pediatr. 2012. 161(6):1016-21. doi:10.1016/j.jpeds.2012.05.049. | Outcome; Population
38 | Englund-Ogge, L, Brantsaeter, AL, Haugen, M, Sengpiel, V, Khatibi, A, Myhre, R, Myking, S, Meltzer, HM, Kacerovsky, M, Nilsen, RM, Jacobsson, B. Association between intake of artificially sweetened and sugar-sweetened beverages and preterm delivery: a large prospective cohort study. Am J Clin Nutr. 2012. 96(3):552-9. doi:10.3945/ajcn.111.031567. | Outcome
39 | Figueiredo, Acmg, Gomes-Filho, IS, Batista, JET, Orrico, GS, Porto, ECL, Cruz Pimenta, RM, Dos Santos Conceicao, S, Brito, SM, Ramos, MSX, Sena, MCF, Vilasboas, Swsl, Seixas da Cruz, S, Pereira, MG. Maternal anemia and birth weight: A prospective cohort study. PLoS One. 2019. 14(3):e0212817. doi:10.1371/journal.pone.0212817. | Intervention/Exposure
40 | Forand, SP, Lewis-Michl, EL, Gomez, MI. Adverse birth outcomes and maternal exposure to trichloroethylene and tetrachloroethylene through soil vapor intrusion in New York State. Environ Health Perspect. 2012. 120(4):616-21. doi:10.1289/ehp.1103884. | Intervention/Exposure
41 | Gilbert-Diamond, D, Emond, JA, Baker, ER, Korrick, SA, Karagas, MR. Relation between in Utero Arsenic Exposure and Birth Outcomes in a Cohort of Mothers and Their Newborns from New Hampshire. Environ Health Perspect. 2016. 124(8):1299-307. doi:10.1289/ehp.1510065. | Intervention/Exposure
42 | Gillman, MW, Rifas-Shiman, SL, Fernandez-Barres, S, Kleinman, K, Taveras, EM, Oken, E. Beverage Intake During Pregnancy and Childhood Adiposity. Pediatrics. 2017. 140(2). doi:10.1542/peds.2017-0031. | Outcome; Population
43 | Giroux, I, Inglis, SD, Lander, S, Gerrie, S, Mottola, MF. Dietary intake, weight gain, and birth outcomes of physically active pregnant women: a pilot study. Appl Physiol Nutr Metab. 2006. 31(5):483-9. doi:10.1139/h06-024. | Intervention/Exposure
44 | Gripp Bicalho, G, de Azevedo Barros Filho, A. Birthweight and caffeine consumption. Revista de Saude Publica. 2002. 36(2):180-187. | Language
45 | Grundt, JH, Nakling, J, Eide, GE, Markestad, T. Possible relation between maternal consumption of added sugar and sugar-sweetened beverages and birth weight--time trends in a population. BMC Public Health. 2012. 12:901. doi:10.1186/1471-2458-12-901. | Study design; Intervention/Exposure
46 | Guinto, VT, Destura, R, Volger, S, Vidal, K, Pecquet, S, Mantaring Iii, JV. Randomized controlled study of nutritional supplement beverages with and without probiotics taken during the third trimester of pregnancy: effects on maternal and fetal outcomes and fetal immune status. International journal of gynaecology and obstetrics. 2015. 131:E358-. | Study design; Publication status
47 | Halicioglu, O, Sutcuoglu, S, Koc, F, Ozturk, C, Albudak, E, Colak, A, Sahin, E, Asik Akman, S. Vitamin B12 and folate statuses are associated with diet in pregnant women, but not with anthropometric measurements in term newborns. J Matern Fetal Neonatal Med. 2012. 25(9):1618-21. doi:10.3109/14767058.2011.648244. | Study design; Intervention/Exposure
48 | Halldorsson, TI, Strom, M, Petersen, SB, Olsen, SF. Intake of artificially sweetened soft drinks and risk of preterm delivery: a prospective cohort study in 59,334 Danish pregnant women. Am J Clin Nutr. 2010. 92(3):626-33. doi:10.3945/ajcn.2009.28968. | Outcome
49 | Heitmann, K, Nordeng, H, Holst, L. Pregnancy outcome after use of cranberry in pregnancy--the Norwegian Mother and Child Cohort Study. BMC Complement Altern Med. 2013. 13:345. doi:10.1186/1472-6882-13-345. | Intervention/Exposure
50 | Hillesund, ER, Bere, E, Haugen, M, Overby, NC. Development of a New Nordic Diet score and its association with gestational weight gain and fetal growth - a study performed in the Norwegian Mother and Child Cohort Study (MoBa). Public Health Nutr. 2014. 17(9):1909-18. doi:10.1017/s1368980014000421. | Intervention/Exposure
51 | Hjelm, C, Harari, F, Vahter, M. Pre- and postnatal environmental boron exposure and infant growth: Results from a mother-child cohort in northern Argentina. Environ Res. 2019. 171:60-68. doi:10.1016/j.envres.2019.01.012. | Intervention/Exposure
52 | Hoffman, CS, Mendola, P, Savitz, DA, Herring, AH, Loomis, D, Hartmann, KE, Singer, PC, Weinberg, HS, Olshan, AF. Drinking water disinfection by-product exposure and fetal growth. Epidemiology. 2008. 19(5):729-37. doi:10.1097/EDE.0b013e3181812bd4. | Intervention/Exposure
53 | Hopenhayn, C, Ferreccio, C, Browning, SR, Huang, B, Peralta, C, Gibb, H, Hertz-Picciotto, I. Arsenic exposure from drinking water and birth weight. Epidemiology. 2003. 14(5):593-602. doi:10.1097/01.ede.0000072104.65240.69. | Intervention/Exposure
54 | Hoyt, AT, Browne, M, Richardson, S, Romitti, P, Druschel, C. Maternal caffeine consumption and small for gestational age births: results from a population-based case-control study. Matern Child Health J. 2014. 18(6):1540-51. doi:10.1007/s10995-013-1397-4. | Study design
55 | Hrolfsdottir, L, Halldorsson, TI, Birgisdottir, BE, Hreidarsdottir, IT, Hardardottir, H, Gunnarsdottir, I. Development of a dietary screening questionnaire to predict excessive weight gain in pregnancy. Matern Child Nutr. 2018. e12639. doi:10.1111/mcn.12639. | Intervention/Exposure
56 | Huang, L, Lerro, C, Yang, T, Li, J, Qiu, J, Qiu, W, He, X, Cui, H, Lv, L, Xu, R, Xu, X, Huang, H, Liu, Q, Zhang, Y. Maternal tea consumption and the risk of preterm delivery in urban China: a birth cohort study. BMC Public Health. 2016. 16:456. doi:10.1186/s12889-016-3100-3. | Outcome
57 | Hutson, JR, Magri, R, Gareri, JN, Koren, G. The incidence of prenatal alcohol exposure in Montevideo Uruguay as determined by meconium analysis. Ther Drug Monit. 2010. 32(3):311-7. doi:10.1097/FTD.0b013e3181dda52a. | Intervention/Exposure
58 | Igra, AM, Harari, F, Lu, Y, Casimiro, E, Vahter, M. Boron exposure through drinking water during pregnancy and birth size. Environ Int. 2016. 95:54-60. doi:10.1016/j.envint.2016.07.017. | Intervention/Exposure
59 | Ileka-Priouzeau, S, Campagna, C, Legay, C, Deonandan, R, Rodriguez, MJ, Levallois, P. Women exposure during pregnancy to haloacetaldehydes and haloacetonitriles in drinking water and risk of small-for-gestational-age neonate. Environ Res. 2015. 137:338-48. doi:10.1016/j.envres.2015.01.005. | Study design; Intervention/Exposure
60 | Infante-Rivard, C. Caffeine intake and small-for-gestational-age birth: modifying effects of xenobiotic-metabolising genes and smoking. Paediatr Perinat Epidemiol. 2007. 21(4):300-9. doi:10.1111/j.1365-3016.2007.00825.x. | Study design
61 | Infante-Rivard, C. Drinking water contaminants, gene polymorphisms, and fetal growth. Environ Health Perspect. 2004. 112(11):1213-6. doi:10.1289/ehp.7003. | Study design; Intervention/Exposure
62 | Iszatt, N, Nieuwenhuijsen, MJ, Bennett, JE, Toledano, MB. Trihalomethanes in public drinking water and stillbirth and low birth weight rates: an intervention study. Environ Int. 2014. 73:434-9. doi:10.1016/j.envint.2014.08.006. | Intervention/Exposure
63 | Jarman, M, Mathe, N, Ramazani, F, Pakseresht, M, Robson, PJ, Johnson, ST, Bell, RC. Dietary Patterns Prior to Pregnancy and Associations with Pregnancy Complications. Nutrients. 2018. 10(7). doi:10.3390/nu10070914. | Outcome
64 | Jarosz, M, Wierzejska, R, Siuba, M. Maternal caffeine intake and its effect on pregnancy outcomes. Eur J Obstet Gynecol Reprod Biol. 2012. 160(2):156-60. doi:10.1016/j.ejogrb.2011.11.021. | Intervention/Exposure
65 | Jen, V, Erler, NS, Tielemans, MJ, Braun, KV, Jaddoe, VW, Franco, OH, Voortman, T. Mothers’ intake of sugar-containing beverages during pregnancy and body composition of their children during childhood: the Generation R Study. Am J Clin Nutr. 2017. 105(4):834-841. doi:10.3945/ajcn.116.147934. | Outcome; Population
66 | Jensen, CB, Berentzen, TL, Gamborg, M, Sorensen, TI, Heitmann, BL. Does prenatal exposure to vitamin D-fortified margarine and milk alter birth weight? A societal experiment. Br J Nutr. 2014. 112(5):785-93. doi:10.1017/s0007114514001330. | Intervention/Exposure; Publication status
67 | Jensen, CB, Stougard, M, Sorensen, TI, Heitmann, BL. Does prenatal exposure to vitamin D-fortified margarine and milk alter birth weight? A societal experiment - CORRIGENDUM. Br J Nutr. 2016. 116(2):377-9. doi:10.1017/s0007114516002014. | Intervention/Exposure; Publication status
68 | Kallen, BA, Robert, E. Drinking water chlorination and delivery outcome-a registry-based study in Sweden. Reprod Toxicol. 2000. 14(4):303-9. | Intervention/Exposure
69 | Kanade, AN, Rao, S, Kelkar, RS, Gupte, S. Maternal nutrition and birth size among urban affluent and rural women in India. J Am Coll Nutr. 2008. 27(1):137-45. | Country
70 | Kaseb, F, Kimiagar, M, Ghafarpoor, M, Valaii, N. Effect of traditional food supplementation during pregnancy on maternal weight gain and birthweight. Int J Vitam Nutr Res. 2002. 72(6):389-93. doi:10.1024/0300-9831.72.6.389. | Intervention/Exposure
71 | Klebanoff, MA, Levine, RJ, Clemens, JD, Wilkins, DG. Maternal serum caffeine metabolites and small-for-gestational age birth. American Journal of Epidemiology. 2002. 155(1):32-37. doi:10.1093/aje/155.1.32. | Intervention/Exposure
72 | Kledmanee, K, Liabsuetrakul, T, Sretrirutchai, S. Risk of adverse pregnancy outcomes and seroprevalence for brucellosis in pregnant women exposed to goats or raw goat products in southern Thailand: a prospective cohort study. BMC Pregnancy Childbirth. 2019. 19(1):118. doi:10.1186/s12884-019-2267-x. | Outcome
73 | Kogevinas, M, Bustamante, M, Gracia-Lavedan, E, Ballester, F, Cordier, S, Costet, N, Espinosa, A, Grazuleviciene, R, Danileviciute, A, Ibarluzea, J, Karadanelli, M, Krasner, S, Patelarou, E, Stephanou, E, Tardon, A, Toledano, MB, Wright, J, Villanueva, CM, Nieuwenhuijsen, M. Drinking Water Disinfection By-products, Genetic Polymorphisms, and Birth Outcomes in a European Mother-Child Cohort Study. Epidemiology. 2016. 27(6):903-11. doi:10.1097/ede.0000000000000544. | Intervention/Exposure
74 | Koletzko, B, Cremer, M, Flothkotter, M, Graf, C, Hauner, H, Hellmers, C, Kersting, M, Krawinkel, M, Przyrembel, H, Robl-Mathieu, M, Schiffner, U, Vetter, K, Weissenborn, A, Wockel, A. Diet and Lifestyle Before and During Pregnancy - Practical Recommendations of the Germany-wide Healthy Start - Young Family Network. Geburtshilfe Frauenheilkd. 2018. 78(12):1262-1282. doi:10.1055/a-0713-1058. | Study design
75 | Lawande, A, Di Gravio, C, Potdar, RD, Sahariah, SA, Gandhi, M, Chopra, H, Sane, H, Kehoe, SH, Marley-Zagar, E, Margetts, BM, Jackson, AA, Fall, CHD. Effect of a micronutrient-rich snack taken preconceptionally and throughout pregnancy on ultrasound measures of fetal growth: The Mumbai Maternal Nutrition Project (MMNP). Matern Child Nutr. 2018. 14(1). doi:10.1111/mcn.12441. | Country
76 | Lawande, A, Gravio, CD, Potdar, RD, Sahariah, SA, Gandhi, M, Chopra, H, Sane, H, Kehoe, SH, Marley-Zagar, E, Fall, CHD. Effect of a micronutrient-rich snack taken pre-conceptionally and throughout pregnancy on ultrasound measures of fetal growth: the Mumbai Maternal Nutrition Project (MMNP). Maternal & child nutrition. 2018. 14. doi:10.1111/mcn.12587. | Country
77 | Lee, BE, Hong, YC, Lee, KH, Kim, YJ, Kim, WK, Chang, NS, Park, EA, Park, HS, Hann, HJ. Influence of maternal serum levels of vitamins C and E during the second trimester on birth weight and length. Eur J Clin Nutr. 2004. 58(10):1365-71. doi:10.1038/sj.ejcn.1601976. | Intervention/Exposure
78 | Lee, HS, Kim, YH, Kwak, HS, Han, JY, Jo, SJ, Lee, HK. Association of Fatty Acid Ethyl Esters in Meconium of Neonates with Growth Deficits at Birth: a Prospective, Single-Centre Cohort Study. J Korean Med Sci. 2018. 33(50):e318. doi:10.3346/jkms.2018.33.e318. | Intervention/Exposure
79 | Lewis, C, Suffet, IH, Ritz, B. Estimated effects of disinfection by-products on birth weight in a population served by a single water utility. Am J Epidemiol. 2006. 163(1):38-47. doi:10.1093/aje/kwj009. | Intervention/Exposure
80 | Limousi, F, Albouy-Llaty, M, Carles, C, Dupuis, A, Rabouan, S, Migeot, V. Does area deprivation modify the association between exposure to a nitrate and low-dose atrazine metabolite mixture in drinking water and small for gestational age? A historic cohort study. Environ Sci Pollut Res Int. 2014. 21(7):4964-73. doi:10.1007/s11356-013-1893-5. | Intervention/Exposure
81 | Liu, X, Wang, X, Tian, Y, Yang, Z, Lin, L, Lin, Q, Zhang, Z, Li, L. Reduced maternal calcium intake through nutrition and supplementation is associated with adverse conditions for both the women and their infants in a Chinese population. Medicine (Baltimore). 2017. 96(18):e6609. doi:10.1097/md.0000000000006609. | Intervention/Exposure; Outcome
82 | Loomans, EM, Hofland, L, van der Stelt, O, van der Wal, MF, Koot, HM, Van den Bergh, BR, Vrijkotte, TG. Caffeine intake during pregnancy and risk of problem behavior in 5- to 6-year-old children. Pediatrics. 2012. 130(2):e305-13. doi:10.1542/peds.2011-3361. | Intervention/Exposure; Outcome
83 | Ludvigsson, JF, Ludvigsson, J. Milk consumption during pregnancy and infant birthweight. Acta Paediatr. 2004. 93(11):1474-8. doi:10.1080/08035250410018319. | Study design
84 | Malhotra, N, Upadhyay, RP, Bhilwar, M, Choy, N, Green, T. The role of maternal diet and iron-folic acid supplements in influencing birth weight: evidence from India’s National Family Health Survey. J Trop Pediatr. 2014. 60(6):454-60. doi:10.1093/tropej/fmu051. | Country
85 | Mantaring, J, Benyacoub, J, Destura, R, Pecquet, S, Vidal, K, Volger, S, Guinto, V. Effect of maternal supplement beverage with and without probiotics during pregnancy and lactation on maternal and infant health: a randomized controlled trial in the Philippines. BMC Pregnancy Childbirth. 2018. 18(1):193. doi:10.1186/s12884-018-1828-8. | Country
86 | Mardones, F, Urrutia, MT, Villarroel, L, Rioseco, A, Castillo, O, Rozowski, J, Tapia, JL, Bastias, G, Bacallao, J, Rojas, I. Effects of a dairy product fortified with multiple micronutrients and omega-3 fatty acids on birth weight and gestation duration in pregnant Chilean women. Public Health Nutr. 2008. 11(1):30-40. doi:10.1017/s1368980007000110. | Intervention/Exposure
87 | Martin, CL, Siega-Riz, AM, Sotres-Alvarez, D, Robinson, WR, Daniels, JL, Perrin, EM, Stuebe, AM. Maternal Dietary Patterns during Pregnancy Are Associated with Child Growth in the First 3 Years of Life. J Nutr. 2016. 146(11):2281-2288. doi:10.3945/jn.116.234336. | Intervention/Exposure
88 | Migeot, V, Albouy-Llaty, M, Carles, C, Limousi, F, Strezlec, S, Dupuis, A, Rabouan, S. Drinking-water exposure to a mixture of nitrate and low-dose atrazine metabolites and small-for-gestational age (SGA) babies: a historic cohort study. Environ Res. 2013. 122:58-64. doi:10.1016/j.envres.2012.12.007. | Intervention/Exposure
89 | Mikkelsen, TB, Osler, M, Orozova-Bekkevold, I, Knudsen, VK, Olsen, SF. Association between fruit and vegetable consumption and birth weight: a prospective study among 43,585 Danish women. Scand J Public Health. 2006. 34(6):616-22. doi:10.1080/14034940600717688. | Intervention/Exposure
90 | Milk as an essential factor in pregnancy. Reproductive biomedicine online. 2006. 12(6):736. | Publication status
91 | Misra, A, Ray, S, Patrikar, S. A longitudinal study to determine association of various maternal factors with neonatal birth weight at a tertiary care hospital. Med J Armed Forces India. 2015. 71(3):270-3. doi:10.1016/j.mjafi.2015.03.001. | Country
92 | Modzelewska, D, Bellocco, R, Elfvin, A, Brantsaeter, AL, Meltzer, HM, Jacobsson, B, Sengpiel, V. Caffeine exposure during pregnancy, small for gestational age birth and neonatal outcome - results from the Norwegian Mother and Child Cohort Study. BMC Pregnancy Childbirth. 2019. 19(1):80. doi:10.1186/s12884-019-2215-9. | Outcome
93 | Moro, GE, Bertino, E, Bravi, F, Tonetto, P, Gatta, A, Quitadamo, PA, Salvatori, G, Profeti, C, Di Nicola, P, Decarli, A, Ferraroni, M, Tavani, A, Stahl, B, Wiens, F. Adherence to the Traditional Mediterranean Diet and Human Milk Composition: Rationale, Design, and Subject Characteristics of the MEDIDIET Study. Front Pediatr. 2019. 7:66. doi:10.3389/fped.2019.00066. | Study design; Outcome; Population
94 | Mostert, D, Steyn, NP, Temple, NJ, Olwagen, R. Dietary intake of pregnant women and their infants in a poor black South African community. Curationis. 2005. 28(4):12-9. doi:10.4102/curationis.v28i4.1002. | Intervention/Exposure; Country
95 | Moussally, K, Berard, A. Exposure to specific herbal products during pregnancy and the risk of low birth weight. Altern Ther Health Med. 2012. 18(2):36-43. | Study design; Intervention/Exposure
96 | Mparmpakas, D, Goumenou, A, Zachariades, E, Pados, G, Gidron, Y, Karteris, E. Immune system function, stress, exercise and nutrition profile can affect pregnancy outcome: Lessons from a Mediterranean cohort. Exp Ther Med. 2013. 5(2):411-418. doi:10.3892/etm.2012.849. | Intervention/Exposure
97 | Murrin, CM, Heinen, MM, Kelleher, CC. Are Dietary Patterns of Mothers during Pregnancy Related to Children’s Weight Status? Evidence from the Lifeways Cross- Generational Cohort Study. AIMS Public Health. 2015. 2(3):274-296. doi:10.3934/publichealth.2015.3.274. | Intervention/Exposure; Population
98 | Myers, SL, Lobdell, DT, Liu, Z, Xia, Y, Ren, H, Li, Y, Kwok, RK, Mumford, JL, Mendola, P. Maternal drinking water arsenic exposure and perinatal outcomes in inner Mongolia, China. J Epidemiol Community Health. 2010. 64(4):325-9. doi:10.1136/jech.2008.084392. | Intervention/Exposure
99 | Nolan, LA, Nolan, JM, Shofer, FS, Rodway, NV, Emmett, EA. Congenital anomalies, labor/delivery complications, maternal risk factors and their relationship with perfluorooctanoic acid (PFOA)-contaminated public drinking water. Reprod Toxicol. 2010. 29(2):147-55. doi:10.1016/j.reprotox.2009.10.012. | Intervention/Exposure
100 | Nolan, LA, Nolan, JM, Shofer, FS, Rodway, NV, Emmett, EA. The relationship between birth weight, gestational age and perfluorooctanoic acid (PFOA)-contaminated public drinking water. Reprod Toxicol. 2009. 27(3-4):231-238. doi:10.1016/j.reprotox.2008.11.001. | Study design; Intervention/Exposure
101 | Ochoa-Acuna, H, Frankenberger, J, Hahn, L, Carbajo, C. Drinking-water herbicide exposure in Indiana and prevalence of small-for-gestational-age and preterm delivery. Environ Health Perspect. 2009. 117(10):1619-24. doi:10.1289/ehp.0900784. | Intervention/Exposure
102 | Okubo, H, Miyake, Y, Sasaki, S, Tanaka, K, Murakami, K, Hirota, Y, Kanzaki, H, Kitada, M, Horikoshi, Y, Ishiko, O, Nakai, Y, Nishio, J, Yamamasu, S, Yasuda, J, Kawai, S, Yanagihara, K, Wakuda, K, Kawashima, T, Narimoto, K, Iwasa, Y, Orino, K, Tsunetoh, I, Yoshida, J, Iito, J, Kaneko, T, Kamiya, T, Kuribayashi, H, Taniguchi, T, Takemura, H, Morimoto, Y, Matsunaga, I, Oda, H, Ohya, Y. Maternal dietary patterns in pregnancy and fetal growth in Japan: the Osaka Maternal and Child Health Study. Br J Nutr. 2012. 107(10):1526-33. doi:10.1017/s0007114511004636. | Intervention/Exposure
103 | Olafsdottir, AS, Magnusardottir, AR, Thorgeirsdottir, H, Hauksson, A, Skuladottir, GV, Steingrimsdottir, L. Relationship between dietary intake of cod liver oil in early pregnancy and birthweight. Bjog. 2005. 112(4):424-9. doi:10.1111/j.14710528.2005.00477.x. | Intervention/Exposure
104 | Olafsdottir, AS, Skuladottir, GV, Thorsdottir, I, Hauksson, A, Steingrimsdottir, L. Maternal diet in early and late pregnancy in relation to weight gain. Int J Obes (Lond). 2006. 30(3):492-9. doi:10.1038/sj.ijo.0803184. | Outcome
105 | Olsen, SF, Halldorsson, TI, Willett, WC, Knudsen, VK, Gillman, MW, Mikkelsen, TB, Olsen, J. Milk consumption during pregnancy is associated with increased infant size at birth: prospective cohort study. Am J Clin Nutr. 2007. 86(4):1104-10. doi:10.1093/ajcn/86.4.1104. | Other
106 | Papadopoulou, E, Botton, J, Brantsæter, AL, Haugen, M, Alexander, J, Meltzer, HM, Bacelis, J, Elfvin, A, Jacobsson, B, Sengpiel, V. Maternal caffeine intake during pregnancy and childhood growth and overweight: Results from a large Norwegian prospective observational cohort study. BMJ Open. 2018. 8(3). doi:10.1136/bmjopen-2017-018895. | Outcome; Population
107 | Parazzini, F, Chiaffarino, F, Chatenoud, L, Tozzi, L, Cipriani, S, Chiantera, V, Fedele, L. Maternal coffee drinking in pregnancy and risk of small for gestational age birth. Eur J Clin Nutr. 2005. 59(2):299-301. doi:10.1038/sj.ejcn.1602052. | Study design
108 | Parvez, S, Gerona, RR, Proctor, C, Friesen, M, Ashby, JL, Reiter, JL, Lui, Z, Winchester, PD. Glyphosate exposure in pregnancy and shortened gestational length: a prospective Indiana birth cohort study. Environ Health. 2018. 17(1):23. doi:10.1186/s12940-018-0367-0. | Intervention/Exposure
109 | Peacock, A, Hutchinson, D, Wilson, J, McCormack, C, Bruno, R, Olsson, CA, Allsop, S, Elliott, E, Burns, L, Mattick, RP. Adherence to the Caffeine Intake Guideline during Pregnancy and Birth Outcomes: A Prospective Cohort Study. Nutrients. 2018. 10(3). doi:10.3390/nu10030319. | Intervention/Exposure
110 | Pedersen, M, Mendez, MA, Schoket, B, Godschalk, RW, Espinosa, A, Landstrom, A, Villanueva, CM, Merlo, DF, Fthenou, E, Gracia-Lavedan, E, van Schooten, FJ, Hoek, G, Brunborg, G, Meltzer, HM, Alexander, J, Nielsen, JK, Sunyer, J, Wright, J, Kovacs, K, de Hoogh, K, Gutzkow, KB, Hardie, LJ, Chatzi, L, Knudsen, LE, Anna, L, Ketzel, M, Haugen, M, Botsivali, M, Nieuwenhuijsen, MJ, Cirach, M, Toledano, MB, Smith, RB, Fleming, S, Agramunt, S, Kyrtopoulos, SA, Lukacs, V, Kleinjans, JC, Segerback, D, Kogevinas, M. Environmental, dietary, maternal, and fetal predictors of bulky DNA adducts in cord blood: a European mother-child study (NewGeneris). Environ Health Perspect. 2015. 123(4):374-80. doi:10.1289/ehp.1408613. | Outcome
111 | Perez-Ferre, N, Fernandez, D, Torrejon, MJ, Del Prado, N, Runkle, I, Rubio, MA, Montanez, C, Bordiu, E, Calle-Pascual, A. Effect of lifestyle on the risk of gestational diabetes and obstetric outcomes in immigrant Hispanic women living in Spain. J Diabetes. 2012. 4(4):432-8. doi:10.1111/j.1753-0407.2012.00221.x. | Intervention/Exposure
112 | Pobocik, RS, Heathcote, GM, Spiers, JB, Otto, CT. Nutritional and anthropometric assessment of a sample of pregnant women and young children in Palau. Asia Pac J Clin Nutr. 2000. 9(2):102-14. | Outcome
113 | Potdar, RD, Sahariah, SA, Gandhi, M, Kehoe, SH, Brown, N, Sane, H, Dayama, M, Jha, S, Lawande, A, Coakley, PJ, Marley-Zagar, E, Chopra, H, Shivshankaran, D, Chheda-Gala, P, Muley-Lotankar, P, Subbulakshmi, G, Wills, AK, Cox, VA, Taskar, V, Barker, DJP, Jackson, AA, Margetts, BM, Fall, CHD. Improving women’s diet quality preconceptionally and during gestation: Effects on birth weight and prevalence of low birth weight - A randomized controlled efficacy trial in India (Mumbai maternal nutrition project). American Journal of Clinical Nutrition. 2014. 100(5):1257-1268. doi:10.3945/ajcn.114.084921. | Country
114 | Rahman, ML, Valeri, L, Kile, ML, Mazumdar, M, Mostofa, G, Qamruzzaman, Q, Rahman, M, Baccarelli, A, Liang, L, Hauser, R, Christiani, DC. Investigating causal relation between prenatal arsenic exposure and birthweight: Are smaller infants more susceptible? Environ Int. 2017. 108:32-40. doi:10.1016/j.envint.2017.07.026. | Intervention/Exposure; Country
115 | Rahman, SM, Kippler, M, Ahmed, S, Palm, B, El Arifeen, S, Vahter, M. Manganese exposure through drinking water during pregnancy and size at birth: A prospective cohort study. Reprod Toxicol. 2015. 53:68-74. doi:10.1016/j.reprotox.2015.03.008. | Country
116 | Rao, S, Yajnik, CS, Kanade, A, Fall, CH, Margetts, BM, Jackson, AA, Shier, R, Joshi, S, Rege, S, Lubree, H, Desai, B. Intake of micronutrient-rich foods in rural Indian mothers is associated with the size of their babies at birth: Pune Maternal Nutrition Study. J Nutr. 2001. 131(4):1217-24. doi:10.1093/jn/131.4.1217. | Country
117 | Rasmussen, KM, Habicht, JP. Maternal supplementation differentially affects the mother and newborn. J Nutr. 2010. 140(2):402-6. doi:10.3945/jn.109.114488. | Study design; Intervention/Exposure
118 | Santos, IS, Matijasevich, A, Valle, NC. Mate drinking during pregnancy and risk of preterm and small for gestational age birth. J Nutr. 2005. 135(5):1120-3. doi:10.1093/jn/135.5.1120. | Study design
119 | Savitz, DA, Stein, CR, Elston, B, Wellenius, GA, Bartell, SM, Shin, HM, Vieira, VM, Fletcher, T. Relationship of perfluorooctanoic acid exposure to pregnancy outcome based on birth records in the mid-Ohio Valley. Environ Health Perspect. 2012. 120(8):1201-7. doi:10.1289/ehp.1104752. | Intervention/Exposure
120 | Shi, X, Ayotte, JD, Onda, A, Miller, S, Rees, J, Gilbert-Diamond, D, Onega, T, Gui, J, Karagas, M, Moeschler, J. Geospatial association between adverse birth outcomes and arsenic in groundwater in New Hampshire, USA. Environ Geochem Health. 2015. 37(2):333-51. doi:10.1007/s10653-014-9651-2. | Intervention/Exposure
121 | Smith, RB, Edwards, SC, Best, N, Wright, J, Nieuwenhuijsen, MJ, Toledano, MB. Birth Weight, Ethnicity, and Exposure to Trihalomethanes and Haloacetic Acids in Drinking Water during Pregnancy in the Born in Bradford Cohort. Environ Health Perspect. 2016. 124(5):681-9. doi:10.1289/ehp.1409480. | Intervention/Exposure
122 | Sokoloff, K, Fraser, W, Arbuckle, TE, Fisher, M, Gaudreau, E, LeBlanc, A, Morisset, AS, Bouchard, MF. Determinants of urinary concentrations of dialkyl phosphates among pregnant women in Canada - Results from the MIREC study. Environ Int. 2016. 94:133-140. doi:10.1016/j.envint.2016.05.015. | Intervention/Exposure; Outcome
123 | Sonnenfeld, N, Hertz-Picciotto, I, Kaye, WE. Tetrachloroethylene in drinking water and birth outcomes at the US Marine Corps Base at Camp Lejeune, North Carolina. Am J Epidemiol. 2001. 154(10):902-8. doi:10.1093/aje/154.10.902. | Intervention/Exposure
124 | Stayner, LT, Almberg, K, Jones, R, Graber, J, Pedersen, M, Turyk, M. Atrazine and nitrate in drinking water and the risk of preterm delivery and low birth weight in four Midwestern states. Environ Res. 2017. 152:294-303. doi:10.1016/j.envres.2016.10.022. | Intervention/Exposure
125 | Sultan Azzeh, F. Risk factors associated with delivering low birth weight infants among pregnant women: A preliminary study in Western Saudi Arabia. Journal of Biological Sciences. 2013. 13(5):417-421. doi:10.3923/jbs.2013.417.421. | Study design
126 | Summerhayes, RJ, Morgan, GG, Edwards, HP, Lincoln, D, Earnest, A, Rahman, B, Beard, JR. Exposure to trihalomethanes in drinking water and small-for-gestational-age births. Epidemiology. 2012. 23(1):15-22. doi:10.1097/EDE.0b013e31823b669b. | Intervention/Exposure
127 | Theroux, R. Caffeine during pregnancy: how much is safe? Nurs Womens Health. 2008. 12(3):240-2. doi:10.1111/j.1751-486X.2008.00329.x. | Study design
128 | Tollanes, MC, Strandberg-Larsen, K, Eichelberger, KY, Moster, D, Lie, RT, Brantsaeter, AL, Meltzer, HM, Stoltenberg, C, Wilcox, AJ. Intake of Caffeinated Soft Drinks before and during Pregnancy, but Not Total Caffeine Intake, Is Associated with Increased Cerebral Palsy Risk in the Norwegian Mother and Child Cohort Study. J Nutr. 2016. 146(9):1701-6. doi:10.3945/jn.116.232272. | Outcome
129 | Turkyilmaz, C, Onal, E, Hirfanoglu, IM, Turan, O, Koc, E, Ergenekon, E, Atalay, Y. The effect of galactagogue herbal tea on breast milk production and short-term catch-up of birth weight in the first week of life. J Altern Complement Med. 2011. 17(2):139-42. doi:10.1089/acm.2010.0090. | Outcome; Population
130 | van der Hoeven, T, Browne, JL, Uiterwaal, Cspm, van der Ent, CK, Grobbee, DE, Dalmeijer, GW. Antenatal coffee and tea consumption and the effect on birth outcome and hypertensive pregnancy disorders. PLoS One. 2017. 12(5):e0177619. doi:10.1371/journal.pone.0177619. | Study design
131 | van Eijsden, M, Hornstra, G, van der Wal, MF, Vrijkotte, TG, Bonsel, GJ. Maternal n-3, n-6, and trans fatty acid profile early in pregnancy and term birth weight: a prospective cohort study. Am J Clin Nutr. 2008. 87(4):887-95. doi:10.1093/ajcn/87.4.887. | Intervention/Exposure
132 | Vik, T, Bakketeig, LS, Trygg, KU, Lund-Larsen, K, Jacobsen, G. High caffeine consumption in the third trimester of pregnancy: gender-specific effects on fetal growth. Paediatr Perinat Epidemiol. 2003. 17(4):324-31. | Study design; Intervention/Exposure
133 | Villanueva, CM, Durand, G, Coutte, MB, Chevrier, C, Cordier, S. Atrazine in municipal drinking water and risk of low birth weight, preterm delivery, and small-for-gestational-age status. Occup Environ Med. 2005. 62(6):400-5. doi:10.1136/oem.2004.016469. | Intervention/Exposure
134 | Vinceti, M, Cann, CI, Calzolari, E, Vivoli, R, Garavelli, L, Bergomi, M. Reproductive outcomes in a population exposed long-term to inorganic selenium via drinking water. Sci Total Environ. 2000. 250(1-3):1-7. | Intervention/Exposure
135 | Vitti, FP, Grandi, C, Cavalli, RC, Simoes, VMF, Batista, RFL, Cardoso, VC. Association between Caffeine Consumption in Pregnancy and Low Birth Weight and Preterm Birth in the birth Cohort of Ribeirao Preto. Rev Bras Ginecol Obstet. 2018. 40(12):749-756. doi:10.1055/s-0038-1675806. | Study design
136 | Voerman, E, Jaddoe, VW, Gishti, O, Hofman, A, Franco, OH, Gaillard, R. Maternal caffeine intake during pregnancy, early growth, and body fat distribution at school age. Obesity (Silver Spring). 2016. 24(5):1170-7. doi:10.1002/oby.21466. | Intervention/Exposure
137 | Wen, LM, Flood, VM, Simpson, JM, Rissel, C, Baur, LA. Dietary behaviours during pregnancy: findings from first-time mothers in southwest Sydney, Australia. International Journal of Behavioral Nutrition & Physical Activity. 2010. 7:7p-7p. doi:10.1186/1479-5868-7-13. | Study design
138 | Wen, LM, Simpson, JM, Rissel, C, Baur, LA. Maternal “junk food” diet during pregnancy as a predictor of high birthweight: findings from the healthy beginnings trial. Birth. 2013. 40(1):46-51. doi:10.1111/birt.12028. | Intervention/Exposure
139 | Wierzejska, R, Jarosz, M, Wojda, B. Caffeine Intake During Pregnancy and Neonatal Anthropometric Parameters. Nutrients. 2019. 11(4). doi:10.3390/nu11040806. | Intervention/Exposure; Outcome
140 | Wright, LS, Rifas-Shiman, SL, Oken, E, Litonjua, AA, Gold, DR. Prenatal and Early Life Fructose, Fructose-Containing Beverages, and Midchildhood Asthma. Ann Am Thorac Soc. 2018. 15(2):217-224. doi:10.1513/AnnalsATS.201707-530OC. | Outcome
141 | Xia, YY, Zhang, H, Gallier, S, Rowan, A, Qi, HB, Baker, PN. Milk fat globule membrane as a source of gangliosides and phospholipids during pregnancy to support healthy pregnancy and birth outcomes. Journal of pediatric gastroenterology and nutrition. 2018. 66:1047-. | Publication status
142 | Xie, Y, Madkour, AS, Harville, EW. Preconception Nutrition, Physical Activity, and Birth Outcomes in Adolescent Girls. J Pediatr Adolesc Gynecol. 2015. 28(6):471-6. doi:10.1016/j.jpag.2015.01.004. | Intervention/Exposure
143 | Xue, F, Willett, WC, Rosner, BA, Forman, MR, Michels, KB. Parental characteristics as predictors of birthweight. Hum Reprod. 2008. 23(1):168-77. doi:10.1093/humrep/dem316. | Study design
144 | Yang, CY, Chang, CC, Tsai, SS, Chuang, HY, Ho, CK, Wu, TN. Arsenic in drinking water and adverse pregnancy outcome in an arseniasis-endemic area in northeastern Taiwan. Environ Res. 2003. 91(1):29-34. | Intervention/Exposure
145 | Yang, CY, Cheng, BH, Tsai, SS, Wu, TN, Lin, MC, Lin, KC. Association between chlorination of drinking water and adverse pregnancy outcome in Taiwan. Environ Health Perspect. 2000. 108(8):765-8. doi:10.1289/ehp.00108765. | Intervention/Exposure
146 | Yang, CY, Chiu, HF, Chang, CC, Wu, TN, Sung, FC. Association of very low birth weight with calcium levels in drinking water. Environ Res. 2002. 89(3):189-94. | Study design; Intervention/Exposure
147 | Yang, CY, Chiu, HF, Tsai, SS, Chang, CC, Sung, FC. Magnesium in drinking water and the risk of delivering a child of very low birth weight. Magnes Res. 2002. 15(3-4):207-13. | Study design; Intervention/Exposure
148 | Yang, CY. Drinking water chlorination and adverse birth outcomes in Taiwan. Toxicology. 2004. 198(1-3):249-54. doi:10.1016/j.tox.2004.01.032. | Intervention/Exposure
149 | Zhang, Z, Tran, NT, Nguyen, TS, Nguyen, LT, Berde, Y, Tey, SL, Low, YL, Huynh, DTT. Impact of maternal nutritional supplementation in conjunction with a breastfeeding support program during the last trimester to 12 weeks postpartum on breastfeeding practices and child development at 30 months old. PLoS One. 2018. 13(7):e0200519. doi:10.1371/journal.pone.0200519. | Country
150 | Zhu, Y, Olsen, SF, Mendola, P, Halldorsson, TI, Rawal, S, Hinkle, SN, Yeung, EH, Chavarro, JE, Grunnet, LG, Granstrom, C, Bjerregaard, AA, Hu, FB, Zhang, C. Maternal consumption of artificially sweetened beverages during pregnancy, and offspring growth through 7 years of age: a prospective cohort study. Int J Epidemiol. 2017. 46(5):1499-1508. doi:10.1093/ije/dyx095. | Health status

vii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).