# List of abbreviations

Abbreviation: Full name
25(OH)D: 25-Hydroxy Vitamin D
AI: Adequate Intake
ALP: Alkaline Phosphatase
BMC: Bone Mineral Content
BMD: Bone Mineral Density
CNPP: Center for Nutrition Policy and Promotion
CTX: C-Terminal Telopeptides
FNS: USDA Food and Nutrition Service
HHS: U.S. Department of Health and Human Services
IU: International Units
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
ONGA: Office of Nutrition Guidance and Analysis
PINP: Procollagen I N-Terminal Propeptide
RDA: Recommended Dietary Allowance
USDA: U.S. Department of Agriculture