# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^vii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 6. Nutrients from Dietary Supplements During Infancy and Toddlerhood.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review question examining vitamin D from supplements consumed during infancy and toddlerhood and bone health. The intervention or exposure of interest is consumption of vitamin D from supplements from birth to 24 months. The comparators are consumption of vitamin D at a different dosage or frequency from supplements, or from fortified foods. The outcomes considered include bone mass, including bone mineral density and bone mineral content, biomarkers of bone metabolism, rickets, and fracture. The key confounders are sex, race/ethnicity, socioeconomic status, parental education, feeding practices (e.g., human milk/infant formula history), use of foods that are fortified or rich in the nutrient of interest (in supplements studies), anthropometry at birth or baseline, and gestational age. The other factors to be considered are vegetarian diet (child), sun exposure and sunscreen usage, maternal vitamin-supplement use, baseline nutrient status, physical activity, and maternal age.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 4 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of vitamin D from supplements; - Studies that specify the dosage/amount of vitamin D received | - Studies that do not specify the dosage/amount level of vitamin D received; - Studies that vary nutrients other than vitamin D without controlling for that variation
Comparator | - Studies that compare consumption of vitamin D; ○ at a different dosage or frequency from supplements; ○ from fortified foods | - N/A
Outcomes | - Bone mass, including:; ○ bone mineral density; ○ bone mineral content; - Biomarkers of bone metabolism; - Rickets; - Fracture | - N/A
Date of publication | - January 2000 – January 2020 | - Articles published prior to 2000
Publication status | - Articles that have been peer-reviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, and conference proceedings)
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^viii^ | - Studies conducted in countries ranked as high or higher human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females | Non-human participants (i.e., animals)
Age of study participants | - Age at intervention or exposure:; ○ Infants and toddlers (0-24 months); - Age at outcome:; ○ Infants and toddlers (0-24 months); ○ Children and adolescents (2-18 years) | - Age at intervention or exposure:; ○ Children and adolescents (2-18 years); ○ Adults (19 years and older); - Age at outcome:; ○ Adults (19 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease or with rickets.; - Studies that enroll infants born full-term (≥37 weeks and 0/7 days gestational age) | - Studies that exclusively enroll participants diagnosed with a disease. (For this criterion, studies that exclusively enroll subjects with obesity were included.); - Studies that exclusively enroll participants with rickets (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest); - Studies that exclusively enroll infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age
Source of Foods, Beverages, or Nutrients | - Vitamin D supplements (e.g., vitamin D drops); - Mother’s own milk; - Commercially prepared infant formula meeting FDA^ix^ and/or Codex Alimentarius^x^ international food standards (e.g., milk-based, soy, partially-hydrolyzed, extensive-hydrolyzed, amino-acid based); - Complementary foods/beverages | - Donor or banked milk; - Infant formulas that do not meet FDA and/or Codex Alimentarius standards

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2000 – January 13, 2020
- Search terms:
  - #1 - vitamin d[Mesh] OR vitamin d [tiab] OR vitamin d3[tiab] OR cholecalciferol[tiab] OR ergocalciferol*[tiab]
  - #2 - (“Bone Density”[Mesh] OR “bone density”[tiab] OR “Bone Development”[Mesh] OR “Bone Development”[tiab] OR osteogenesis[tiab] OR “Fractures, Bone”[Mesh] OR osteitis[tiab] OR bone turnover[tiab] OR bone loss[tiab] OR (bone[tiab] AND fracture*[tiab]) OR rickets [mesh] OR ricket*[tiab] OR bone mineral*[tiab] OR bone mass[tiab] OR bone health[tiab] OR bone demineral*[tiab]) OR ((bone[tiab] OR bones[tiab] OR “Bone and Bones”[Mesh] OR bone diseases[mh] OR bone development[Mesh]) AND (remodel*[tiab] OR form*[tiab] OR osteolysis[tiab] OR ossification[tiab] OR resorption[tiab] OR accretion[tiab] OR bmc[tiab] OR bmd[tiab] OR “Biomarkers”[Mesh] OR biomarker*[tiab]))
  - #3 - dietary supplements[Mesh] OR supplement*[tiab] OR drops[tiab] OR multivitamin*[tiab]
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh]))
  - #6 - #4 NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])
    Publication Date Filters: Publication date from 2000/01/01 to 2020/01/13; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2000- January 13, 2020
- Search terms:
  - #1 - “vitamin d” OR [mh “vitamin d”[mj]] OR “vitamin d3” OR cholecalciferol OR ergocalciferol*
  - #2 - ([mh “Bone Density”[mj]] OR “bone density” OR [mh “Bone Development”[mj]] OR “Bone Development” OR osteogenesis OR [mh “Fractures, Bone”[mj]] OR [mh “Bone Diseases”[mj]] OR osteitis OR “bone turnover” OR “bone loss” OR (bone AND fracture*) OR ricket* OR “bone mineral*” OR “bone mass” OR “bone health” OR “bone demineral*”) OR ((bone OR bones) NEAR/5 (remodel* OR form* OR osteolysis OR ossification OR resorption OR accretion OR bmc OR bmd OR biomarker* OR [mh “Biological Markers”])):ti,ab,kw
  - #3 - [mh “dietary supplement”] OR supplement* OR drops OR multivitamin*
    Filters: Publication Year from 2000 to 2020, Trials

#### Embase

- Provider: Elsevier
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2000 – January 13, 2020
- Search terms:
  - #1 - ‘vitamin d’/exp/mj OR ‘vitamin d*’:ab,ti OR ‘vitamin d3’:ti,ab OR cholecalciferol:ab,ti OR ergocalciferol*:ab,ti
  - #2 - (((bone OR bones) NEAR/6 (remodel* OR form* OR osteolysis OR ossification OR resorption OR accretion OR bmc OR bmd OR biomarker*)):ab,ti) OR ((bone NEAR/6 fracture*):ab,ti) OR ‘bone density’:ab,ti OR ‘bone development’:ab,ti OR osteogenesis:ab,ti OR osteitis:ab,ti OR ‘bone turnover’:ab,ti OR ‘bone loss’:ab,ti OR ricket*:ab,ti OR ‘bone mineral*’:ab,ti OR ‘bone mass’:ab,ti OR ‘bone health*’:ab,ti OR ‘bone demineral*’:ab,ti OR ‘bone density’/exp/mj OR ‘bone development’/exp/mj OR ‘fracture’/exp/mj OR ‘bone disease’/exp/mj
  - #3 - ‘dietary supplement’/exp OR supplement*:ti,ab OR drops:ti,ab OR multivitamin*:ti,ab OR ‘multivitamin’/exp
  - #4 - #1 AND #2 AND #3
  - #5 - #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index to Nursing and Allied Health Literature (CINAHL Plus)

- Provider: Ebscohost
- Date(s) Searched: January 13, 2020
- Date range searched: January 1, 2000- January 13, 2020
- Search terms:
  - #1 - “vitamin d” OR “vitamin d3” OR (MH “vitamin d”) OR cholecalciferol OR ergocalciferol*
  - #2 - (MH “Bone Density”) OR “bone density” OR (MH “Bone Development”) OR “Bone Development” OR osteogenesis OR (MH “Fractures, Bone”) OR (MH “Bone Diseases”) OR osteoporosis OR osteopenia OR osteitis OR “bone turnover” OR “bone loss” OR (bone AND fracture*) OR ricket* OR “bone mineral*” OR “bone mass” OR “bone health*” OR “bone demineral*” OR ((bone OR bones) N5 (remodel* OR form* OR osteolysis OR ossification OR resorption OR accretion OR bmc OR bmd OR biomarker*)) OR (bone* AND (MH “Biological Markers+”)
  - #3 - (MH “dietary supplements”) OR supplement* OR drops OR multivitamin*
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication)
    Filters: Published Date: 20000101 to 20200113, English, Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 5 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they met criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

The electronic search of PubMed, Embase, Cochrane, and CINAHL retrieved 8045 records. After the removal of duplicates 4581 titles were screened. Of these, 4128 were excluded and 453 moved on to abstract screening. Of the 453 abstracts screened, 414 were excluded and 39 moved on to full-text sreening. Of the 39 full-text articles, 34 were excluded and 5 were included in the systematic review. One additional article was included from a manual search, resulting in 6 articles total.

### Excluded articles

Table 5 Articles excluded after full text screening with rationale for exclusion

The table below lists the articles excluded after full-text screening. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

| Full texts screened | Rationale for exclusion
1 | Abrams, S. A.,Hawthorne, K. M.,Rogers, S. P.,Hicks, P. D.,Carpenter, T. O. (2012). Effects of ethnicity and vitamin D supplementation on vitamin D status and changes in bone mineral content in infants BMC Pediatr, 12, 6 | Intervention/exposure vs comparator
2 | Bagnoli, F.,Casucci, M.,Toti, S.,Cecchi, S.,Iurato, C.,Coriolani, G.,Tiezzi, M.,Vispi, L. (2013). Is vitamin D supplementation necessary in healthy full-term breastfed infants? A follow-up study of bone mineralization in healthy full-term infants with and without supplemental vitamin D Minerva Pediatr, 65(3), 253-60 | Study design
3 | Bly, E.,Huntington, J.,Harper, A. L.,Vincent, E. C. (2013). What is the best age to start vitamin D supplementation to prevent rickets in breastfed newborns? Journal of Family Practice, 62(12), 755+763 | Study design
4 | Czech-Kowalska, J.,Pludowski, P.,Dobrzanska, A.,Kryskiewicz, E.,Karczmarewicz, E.,Gruszfeld, D.,Pleskaczynska, A.,Golkowska, M. (2012). Impact of vitamin D supplementation on markers of bone mineral metabolism in term infants Bone, 51(4), 781-6 | Intervention/exposure vs comparator
5 | Gallo, S.,Rodd, C.,Vanstone, C.,Agellon, S.,L’Abbe, M.,Khamessan, A.,Weiler, H. (2011). Lumbar spine bone mineral density is enhanced in breast fed infants receiving 800 or 1200 IU of vitamin d daily from 4 to 20 weeks of age Journal of bone and mineral research, 26 | Publication status
6 | Hazell, T. J.,Gallo, S.,Vanstone, C. A.,Agellon, S.,Rodd, C.,Weiler, H. A. (2017). Vitamin D supplementation trial in infancy: body composition effects at 3 years of age in a prospective follow-up study from Montréal Pediatric obesity, 12(1), 38-47 | Outcome
7 | Jackson, R. D.,LaCroix, A. Z.,Gass, M.,Wallace, R. B.,Robbins, J.,Lewis, C. E.,Bassford, T.,Beresford, S. A. A.,Black, H. R.,Blanchette, P.,Bonds, D. E.,Brunner, R. L.,Brzyski, R. G.,Caan, B.,Cauley, J. A.,Chlebowski, R. T.,Cummings, S. R.,Granek, I.,Hays, J.,Heiss, G. (2006). Calcium plus vitamin D supplementation and the risk of fractures [corrected] [published erratum appears in N ENGL J MED 2006 Mar 9;354(10):1102] New England Journal of Medicine, 354(7), 669-683 | Participant age
8 | Jin, J. (2018). Vitamin D and Calcium Supplements for Preventing Fractures Jama, 319(15), 1630 | Publication status
9 | Jorde, R.,Stunes, A. K.,Kubiak, J.,Joakimsen, R.,Grimnes, G.,Thorsby, P. M.,Syversen, U. (2019). Effects of vitamin D supplementation on bone turnover markers and other bone-related substances in subjects with vitamin D deficiency Bone, 124, 7-13 | Participant age
10 | Jorde, R.,Strand Hutchinson, M.,Kjærgaard, M.,Sneve, M.,Grimnes, G. (2013). Supplementation with high doses of vitamin D to subjects without vitamin D deficiency may have negative effects: Pooled data from four intervention trials in Tromsø ISRN Endocrinology, 1(1) | Study design
11 | Kim, M. J.,Na, B.,No, S. J.,Han, H. S.,Jeong, E. H.,Lee, W.,Han, Y.,Hyeun, T. (2010). Nutritional status of vitamin D and the effect of vitamin D supplementation in Korean breast-fed infants J Korean Med Sci, 25(1), 83-9 | Intervention/exposure vs comparator
12 | LeFevre, M. K. (2010). Rickets: A Preventable Growth Delay Journal of Pediatric Healthcare, 24(6), 408-412 | Publication status, Participant health
13 | McAllister, J. C.,Lane, A. T.,Buckingham, B. A. (2006). Vitamin D deficiency in the San Francisco Bay Area J Pediatr Endocrinol Metab, 19(3), 205-8 | Study design
14 | Morandi, G.,Maines, E.,Piona, C.,Monti, E.,Sandri, M.,Gaudino, R.,Boner, A.,Antoniazzi, F. (2015). Significant association among growing pains, vitamin D supplementation, and bone mineral status: results from a pilot cohort study J Bone Miner Metab, 33(2), 201-6 | Participant age
15 | Mutlu, G. Y.,Kusdal, Y.,Ozsu, E.,Cizmecioglu, F. M.,Hatun, S. (2011). Prevention of Vitamin D deficiency in infancy: daily 400 IU vitamin D is sufficient Int J Pediatr Endocrinol, 2011(1), 4 | Intervention/exposure vs comparator, Outcome
16 | Ponnapakkam, T.,Bradford, E.,Gensure, R. (2010). Vitamin D supplementation in breastfed infants: results of a prospective trial in the southern United States Journal of bone and mineral research., 25, S232 | Publication status
17 | Ponnapakkam, T.,Bradford, E.,Gensure, R. (2010). A treatment trial of vitamin d supplementation in breast-fed infants: Universal supplementation is not necessary for rickets preventio in southern louisiana Clinical Pediatrics, 49(11), 1053-1060 | Duplicate
18 | Rangarajan, R.,Mondal, S.,Thankachan, P.,Chakrabarti, R.,Kurpad, A. V. (2018). Assessing bone mineral changes in response to vitamin D supplementation using natural variability in stable isotopes of Calcium in Urine Sci Rep, 8(1), 16751 | Participant age
19 | Rooze, S.,Mathieu, F.,Claus, W.,Yangzom, T.,Yangzom, D.,Goyens, P.,de Maertelaer, V. (2016). Effect of calcium and vitamin D on growth, rickets and Kashin-Beck disease in 0- to 5-year-old children in a rural area of central Tibet Trop Med Int Health, 21(6), 768-75 | Intervention/exposure vs comparator
20 | Savino, F.,Viola, S.,Tarasco, V.,Lupica, M. M.,Castagno, E.,Oggero, R.,Miniero, R. (2011). Bone mineral status in breast-fed infants: influence of vitamin D supplementation Eur J Clin Nutr, 65(3), 335-9 | Study design
21 | Sen, S.,Penfield-Cyr, A.,Hollis, B. W.,Wagner, C. L. (2017). Maternal Obesity, 25-Hydroxy Vitamin D Concentration, and Bone Density in Breastfeeding Dyads J Pediatr, 187, 147-152.e1 | Intervention/exposure vs comparator
22 | Shaikh, U.,Alpert, P. T. (2006). Nutritional rickets in Las Vegas, Nevada J Pediatr Endocrinol Metab, 19(3), 209-12 | Study design
23 | Thorisdottir, B.,Gunnarsdottir, I.,Steingrimsdottir, L.,Palsson, G. I.,Thorsdottir, I. (2014). Vitamin D intake and status in 12-month-old infants at 63-66° N Nutrients, 6(3), 1182-1193 | Study design
24 | Torjesen, I. (2018). Vitamin D supplements do not protect bone health, analysis finds Bmj, 363, k4223 | Publication status
25 | Valkama, S., Holmlund-Suila, E., Enlund-Cerullo, M.,Rosendahl, J.,Hauta-Alus, H.,Helve, O.,Hytinantti, T.,Viljakainen,H.,Andersson, S.,Makitie, O. (2017). No Severe Hypercalcemia with Daily Vitamin D3 Supplementation of up to 30 microg during the First Year of Life Horm Res Paediatr, 88(2), 147-154 | Outcome
26 | Valkama, S.,Holmlund-Suila, E.,Enlund-Cerullo, M.,Rosendahl, J.,Hauta-Alus, H.,Helve, O.,Hytinantti, T.,Viljakainen, H.,Andersson, S.,Mäkitie, O. (2017). No Severe Hypercalcemia with Daily Vitamin D3 Supplementation of up to 30 µg during the First Year of Life Hormone research in paediatrics, 88(2), 147-154 | Duplicate
27 | van den Hooven, E. H.,Heppe, D. H.,Kiefte-de Jong, J. C.,Medina-Gomez, C.,Moll, H. A.,Hofman, A.,Jaddoe, V. W.,Rivadeneira, F.,Franco, O. H. (2015). Infant dietary patterns and bone mass in childhood: the Generation R Study Osteoporos Int, 26(5), 1595-604 | Intervention/exposure vs comparator
28 | Viljakainen, H. T.,Korhonen, T.,Hytinantti, T.,Laitinen, E. K.,Andersson, S.,Makitie, O.,Lamberg-Allardt, C. (2011). Maternal vitamin D status affects bone growth in early childhood--a prospective cohort study Osteoporos Int, 22(3), 883-91 | Intervention/exposure vs comparator
29 | Viljakainen, H. T.,Korhonen, T.,Hytinantti, T.,Laitinen, E. K. A.,Andersson, S.,Mäkitie, O.,Lamberg-Allardt, C. (2011). Maternal vitamin D status affects bone growth in early childhood-a prospective cohort study Osteoporosis International, 22(3), 883-891 | Duplicate
30 | Wicklow, B.,Gallo, S.,Majnemer, A.,Vanstone, C.,Comeau, K.,Jones, G.,L’Abbe, M.,Khamessan, A.,Sharma, A.,Weiler, H.,Rodd, C. (2016). Impact of Vitamin D Supplementation on Gross Motor Development of Healthy Term Infants: A Randomized Dose-Response Trial Phys Occup Ther Pediatr, 36(3), 330-42 | Outcome
31 | (2012). Boning up on calcium and vitamin D. Do you need supplements to preserve your bone health? Johns Hopkins Med Lett Health After 50, 24(9), 1-2 | Publication status
32 | (2006). Calcium and vitamin D supplements Med Lett Drugs Ther, 48(1240), 61 | Study design
33 | (2006). Calcium + vitamin D offers small bone improvements. But these supplements do not significantly reduce the risk of fractures Health News, 12(5), 6-7 | Publication status
34 | (2011). How much vitamin D do you need? Johns Hopkins Med Lett Health After 50, 23(2), 7 | Publication status

vii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

ix U.S. Food and Drug Administration. Version 19 December 2013. Internet: https://www.fda.gov/Food/GuidanceRegulation/GuidanceDocumentsRegulatoryInformation/InfantFormula/ucm136118.htm#manufacture (accessed March 23, 2018).

x Food and Agriculture Organization of the United Nations. World Health Organization. Codex Alimentarius. International Food Standards. Standard for infant formula and formulas for special medical purposes intended for infants. Codex Stan 72-1981. 2007.