# WHAT IS THE RELATIONSHIP BETWEEN VITAMIN D FROM SUPPLEMENTS CONSUMED DURING INFANCY AND TODDLERHOOD AND BONE HEALTH?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between vitamin D from supplements consumed during infancy and toddlerhood and bone health?

### What is the answer to the question?

- Limited evidence suggests no relationship between consumption of 400 IU per day of vitamin D from supplements before age 12 months, compared with higher dosages of up to 1600 IU per day, and biomarkers of bone metabolism in children up to age 36 months.
- Insufficient evidence is available to determine the relationship between 400 IU per day of vitamin D from supplements, compared with higher dosages, and bone mass, rickets, or fracture.
- Insufficient evidence is available to determine the relationship between 400 IU per day of vitamin D from supplements, compared with lower dosages, and bone mass, biomarkers of bone metabolism, rickets, or fracture.
- Insufficient evidence is available to determine the relationship between vitamin D from supplements, compared with no vitamin D from supplements, and bone mass, biomarkers of bone metabolism, rickets, or fracture.
- Insufficient evidence is available to determine the relationship between vitamin D from supplements, compared with vitamin D from fortified foods, and bone mass, biomarkers of bone metabolism, rickets, or fracture.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee, conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- Vitamin D supplementation was examined in healthy infants and toddlers (birth to 24 months) with outcomes measured at birth through age 18 years.

### What evidence was found?

- This review includes 6 articles.
- The articles compared infants and toddlers who consumed different dosages of vitamin D from supplements. Most articles compared infants supplemented with 400 International Units (IU) per day (which is the Adequate Intake for infants) with infants supplemented with higher dosages.
- The outcomes of interest were bone mass, biomarkers of bone metabolism, rickets, and fracture from birth to age 18 years. Most articles examined bone mass and biomarkers of bone metabolism in children up to age 36 months.
- Limited evidence suggests that infants who are supplemented with 400 IU per day and infants who are supplemented with higher dosages of up to 1600 IU per day do not have differences in biomarkers of bone metabolism up to age 36 months, but the evidence related to bone mass was inconsistent.
- There are limitations in the evidence as follows:
  ○ There were not a lot of articles, and some of the articles studied groups of infants and toddlers that may have been too small to detect a relationship between iron supplementation and growth or size.
  ○ The studies examined infants who were given supplements for different lengths of time, examined different biomarkers of bone metabolism, and measured the biomarkers at different ages, so comparing the findings of the studies was difficult.
  ○ In the studies that reported race, most or all infants were white. The findings may or may not be the same in other racial or ethnic groups.

### How up-to-date is this systematic review?

- This review searched for studies from January, 2000 to January, 2020

## FULL REVIEW

### Systematic review question

What is the relationship between vitamin D from supplements consumed during infancy and toddlerhood and bone health?

### Conclusion statements and grades

Limited evidence suggests no relationship between consumption of 400 IU per day of vitamin D from supplements before age 12 months, compared with higher dosages of up to 1600 IU per day, and biomarkers of bone metabolism in children up to age 36 months. (Grade: Limited)

Insufficient evidence is available to determine the relationship between 400 IU per day of vitamin D from supplements, compared with higher dosages, and bone mass, rickets, or fracture. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between 400 IU per day of vitamin D from supplements, compared with lower dosages, and bone mass, biomarkers of bone metabolism, rickets, or fracture. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between vitamin D from supplements, compared with no vitamin D from supplements, and bone mass, biomarkers of bone metabolism, rickets, or fracture. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between vitamin D from supplements, compared with vitamin D from fortified foods, and bone mass, biomarkers of bone metabolism, rickets, or fracture. (Grade: Grade not assignable)

### Summary of the evidence

- Six articles met the inclusion criteria for this systematic review,^1–6^ which presented evidence from 5 independent randomized controlled trials (1 research group published 2 articles about the same trial).
- The intervention of interest was vitamin D from supplements consumed during infancy or toddlerhood. Dietary supplements are products that contain one or more dietary ingredients (in this case, vitamin D) intended to be taken by mouth to supplement the diet.^ii^ In the United States, 400 IU of vitamin D per day is the AI for infants younger than age 12 months, whereas the RDA for ages 12 to 24 months of age is 600 IU per day. To meet this need, the American Academy of Pediatrics currently recommends a supplement of 400 IU per day for infants fed human milk (with the possible exception of infants whose mothers are taking supplements of about 6000 IU per day^iii^; maternal vitamin D supplementation during lactation was outside of the scope of this systematic review).
- The comparators of interest were different dosages of vitamin D from supplements and vitamin D from fortified foods. However, no articles were identified that included fortified food comparators.
- The outcomes of interest were bone mass, biomarkers of bone metabolism, rickets, and fracture through adolescence (i.e., birth through age 18 years), However, no articles were identified that examined fracture or outcomes beyond 36 months.
- Limited evidence from 3 studies suggests no relationship between 400 IU per day of vitamin D from supplements, compared with higher dosages, and biomarkers of bone metabolism in children up to age 36 months. The ability to draw a stronger conclusion was primarily limited by a small number of studies, small sample sizes, heterogeneous methods, and limited generalizability.
- Evidence available from 4 studies was insufficient to determine whether a relationship exists between 400 IU per day of vitamin D from supplements, compared with higher dosages, and bone mass. The ability to draw a conclusion was hindered by inconsistent findings from a small number of studies. No studies were available that examined the relationship between 400 IU per day of vitamin D from supplements, compared with higher dosages, and rickets or bone fracture.
- Evidence available from 1 study was insufficient to determine whether a relationship exists between 400 IU per day of vitamin D from supplements, compared with lower dosages, and bone mass or biomarkers of bone metabolism. No studies were available that examined the relationship between 400 IU per day of vitamin D from supplements, compared with lower dosages, and rickets or fracture.
- Evidence available from 1 study was insufficient to determine whether a relationship exists between 200 IU per day of vitamin D from supplements for different durations, compared with no vitamin D from supplements, and biomarkers of bone metabolism or rickets. No studies were available that examined the relationship between 200 IU per day of vitamin D from supplements for different durations, compared with no vitamin D from supplements, and bone mass or fracture. No studies were available that compared other dosages of vitamin D from supplements with no supplementation. It is likely that the evidence that led to the current supplementation recommendation pre-dates our literature search date range of January 2000 to January 2020.

### Description of the evidence

This systematic review examines available evidence about the relationship between vitamin D from supplements consumed during infancy and toddlerhood and bone health from birth through adolescence.

Six articles, published between 2010 and 2018, met the inclusion criteria.^1–6^ The 6 articles present evidence from 5 independent randomized controlled trials; the 2 articles by Gallo et al^1,2^ are from the same study.

#### Population

Study participants were from the United States,^4,6^ Canada,^1,2^ and Finland.^3,5^ In 3 studies, the participants were predominantly or entirely White,^1,2,5,6^ and the remaining 2 studies did not report race or ethnicity.^3,4^

Baseline vitamin D status was similar in 3 studies, with serum 25-hydroxy vitamin D [25(OH)D] averaging 50-56 nmol/L.^1–4^ Rosendahl et al^5^ reported that for the majority of infants (52%), the range was 75-125 nmol/L 25(OH)D. Ziegler et al^6^ did not report baseline vitamin D concentrations.

The studies focused on infants fed human milk. Intake of infant formula, dietary sources of vitamin D, and sun exposure varied between studies (Table 1).

Table 1 Infant feeding and dietary and environmental sources of vitamin D

Study | Human milk and infant formula | Dietary vitamin D | Sun exposure
Gallo et al ^1^ ^,^ ^2^ | - Recruited infants <1 month consuming ≥80% total milk volume as human milk; 88% and 35% consumed any human milk at 6 and 12 months, respectively; - Average formula intake increased from 35 g/d at 1 month to 155 g/d at 6 months and 252 g/d by 12 months | - Average dietary intake of vitamin D increased from 43 IU/d at 1 month to 84 IU/d at 6 months and 245 IU/d by 12 months; - Average dietary intake of vitamin D was 247-302 IU/d at 36 months, depending on the group | - Average sun exposure (estimated as h/wk * % exposed body surface area) increased from 7 at 1 month to a peak of 71 at 9 months and then decreased to 56 at 12 months; at 36 months it was 1.6-1.7 depending on the group; - About half (56%) of infants were born during the “synthesizing period” of April to October when cutaneous vitamin D production is possible based on latitude; - The majority of children (84-96% depending on the group) had fair or very fair skin color
Holmlund-Suila et al ^3^ | - Infant feeding at recruitment not reported; - At the time of the outcome measure (3 months), 95% of infants were consuming human milk; - At the time of the outcome measure (3 months) mean formula intake was 2.5 L/wk | - Not reported; however, infants were only 3 months old by the end of the study | - Not reported; however infants were born in September to February in Finland and followed for 3 months
Ponnapakkam et al ^4^ | - Recruited newborns whose mothers intended to feed >50% human milk for 3 months; - Excluded infants consuming >50% infant formula ≤ 3 months (36% of participants) | - Not reported | - Not reported; however infants resided in southern Louisiana, and 7 of 25 participants who completed the study were described as “high risk” based on the presence of risk factors such as dark skin color or full-body clothing/draping
Rosendahl et al ^5^ | - The majority (79%) of infants were fed human milk >6 months; - Formula intake was not reported | - Average dietary intake of vitamin D was 248 IU/d at 12 months, and not reported at other ages | - Not reported; however, authors describe the population as “northern European with limited sunlight exposure”; - All infants were of northern European ethnicity
Ziegler et al ^6^ | - Recruited infants <28 days fed human milk exclusively; - Caregivers encouraged not to introduce infant formula until >9 months | - Not reported | - All infants Caucasian; - Outcomes measured at the end of winter

#### Interventions and comparators

The intervention was vitamin D from supplements consumed during infancy and toddlerhood. In all 5 studies, vitamin D was provided in the form of vitamin D3 drops.

Four studies compared 400 IU/d of vitamin D with higher dosages:

1. Gallo et al^1,2^ compared dosages of 400, 800, 1200, and 1600 IU/d from 1 to 12 months of age (i.e., nearly 1 year of supplementation)
2. Holmlund-Suila et al^3^ compared dosages of 400, 1200, and 1600 IU/d from 2 weeks to 3 months of age (i.e., 2.5 months of supplementation)
3. Rosendahl et al^5^ compared dosages of 400 and 1200 IU/d from 2 weeks to 24 months of age (i.e., nearly 2 years of supplementation)
4. Ziegler et al^6^ compared 400, 600, and 800 IU/d from 2 to 9 months (i.e., 7 months of supplementation)

One study compared 400 IU/d with a lower dosage: Ziegler et al^6^ compared 400 and 200 IU/d from 2 to 9 months (i.e., 7 months of supplementation).

One study compared 200 IU/d for different durations with a placebo: Ponnapakkam et al^4^ compared 200 IU/d from birth to 6 months (i.e., 6 months of supplementation), 200 IU/d from 2 to 6 months (i.e., 4 months of supplementation), and placebo from birth to 6 months.

#### Outcomes

Four studies assessed bone mass outcomes:

1. Gallo et al^1,2^ reported:
  - Femur, lumbar spine, and whole-body bone mineral content (BMC) at 3, 6, 9, and 12 months, and change in femur, lumbar spine, and whole-body BMC from 1 to 3, 3 to 6, 6 to 9, and 9 to 12 months
  - Lumbar spine and whole-body BMC 36 months, change in lumbar spine and whole-body BMC from 12 to 36 and 1 to 36 months, and lumbar spine and whole-body bone mineral density (BMD) and BMD z-score at 36 months
2. Holmlund-Suila et al^3^ reported:
  - Total and trabecular bone and cortical bone BMD and cross-sectional area at 3 months, and polar stress and strain index (an indicator of bone strength) at 3 months
3. Rosendahl et al^5^ reported:
  - Total bone and cortical bone BMC, BMD, cross-sectional area, and polar moment of inertia at 24 months
4. Ziegler et al^6^ reported:
  - Whole-body BMC and BMD at the end of winter (i.e., infant ages 5.5-9 months) and in subsamples of infants who were 5.5, 7.5, and 9 months at end of winter

Four studies assessed biomarkers of bone formation and bone resorption:

- Bone formation biomarkers
  - Alkaline phosphatase (ALP) at 2, 4, and 6 months^4^ and 4, 5.5, 7.5, and 9 months^6^
  - Osteocalcin at 4, 5.5, 7.5, and 9 months^6^
  - Procollagen I N-terminal propeptide (PINP) at 3 months^3^
- Bone resorption biomarkers
  - C-terminal telopeptides (CTX) at 3 months^3^; 4, 5.5, 7.5, and 9 months^6^; and 36 months^2^

One study assessed rickets: Ponnapakkam et al^4^ reported the incidence of rickets at 2, 4, and 6 months.

### Synthesis and assessment^iv^ of the evidence

#### Comparisons of 400 IU/d with higher dosages of vitamin D

Four of the 5 studies compared 400 IU/d of vitamin D with higher dosages.^1–3,5,6^ The Adequate Intake (AI) for infants is 400 IU/d of vitamin D and the Recommended Dietary Allowance (RDA) for children ages 1 year and older is 600 IU/d.^v^ To meet this need, the American Academy of Pediatrics currently recommends a supplement of 400 IU/d for human milk-fed infants (with the possible exception of infants whose mothers are taking supplements of about 6000 IU/d).^vi^

All 4 studies examined bone mass outcomes, and 3 examined biomarkers of bone metabolism.

##### Bone Mass

The evidence was inconsistent with regard to the statistical significance of the findings and the direction of the statistically significant relationships. These inconsistencies are outlined below.

Holmlund-Suila et al^3^ reported significant positive relationships and Ziegler et al^6^ reported significant inverse relationships between vitamin D dosage and bone mass in infants:

- Holmlund-Suila et al^3^ compared infants given 400, 1200, and 1600 IU/d of vitamin D3 from 2 weeks to 3 months of age. Infants given 1600 IU/d had: (a) significantly higher total and trabecular bone cross-sectional area at 3 months than infants given 400 IU/d (but not 1200 IU/d); (b) significantly higher cortical bone cross-sectional area at 3 months than infants given 400 or 1200 IU/d; and (c) significantly higher polar stress and strain index at 3 months than infants given 400 or 1200 IU/d. There were no significant differences in total and trabecular bone or cortical bone BMD at 3 months.
- Ziegler et al^6^ compared infants given 400, 600, and 800 IU/d of vitamin D3 from 2 to 9 months of age. Infants given 600 IU/d had: (a) significantly lower whole-body BMC at the end of winter (i.e., 5.5-9 months) than infants given 400 IU/d, and (b) significantly lower whole-body BMD at the end of winter than infants given 400 IU/d. There were also no significant differences between infants given 800 IU/d and smaller dosages.

Gallo et al^1,2^ and Rosendahl et al^5^ did not report significant differences in bone mass between infants given different dosages of vitamin D:

- Gallo et al^1,2^ compared infants given 400, 800, 1200, and 1600 IU/d of vitamin D3 from 1 to 12 months of age. No significant differences were observed in: (a) femur, lumbar spine, and whole-body BMC at 3, 6, 9, and 12 months, (b) change in femur, lumbar spine, and whole-body BMC from 1 to 3, 3 to 6, 6 to 9, and 9 to 12 months, (c) lumbar spine and whole-body BMC 36 months, (d) change in lumbar spine and whole-body BMC from 12 to 36 and 1 to 36 months, and (e) lumbar spine and whole-body BMD and BMD z-score at 36 months. It is possible that the lack of statistical significance is related to power. Study authors calculated that 25 participants per group would be sufficient to detect a 5% difference in whole-body BMD, and at the 36-month outcome measure, the analytic groups had between 6 and 25 participants, depending on the assessment.
- Rosendahl et al^5^ compared infants given 400 and 1200 IU/d of vitamin D3 from 2 weeks to 24 months and reported no significant differences in total bone and cortical bone BMC, BMD, cross-sectional area, and polar moment of inertia at 24 months. It is unlikely that the lack of statistical significance was related to power. Study authors calculated that 210 participants per group would permit detection of 0.2 SD difference in BMC and 297 participants per group would permit detection of 0.2 SD difference in the cross-sectional area; analytic groups were larger than these estimations (N=343 and 361).

Given the small number of studies and the inconsistency in results, there is insufficient evidence to determine the relationship between 400 IU/d of vitamin D from supplements, compared with higher dosages of vitamin D from supplements, and bone mass.

##### Biomarkers of bone metabolism

The evidence had strong consistency. None of the studies found significant differences in biomarkers of bone metabolism between different dosages and durations of vitamin D supplementation.

Bone resorption biomarkers:

- Holmlund-Suila et al^3^ compared dosages of 400, 1200, and 1600 IU/d from 2 weeks to 3 months and found no significant differences in CTX at 3 months
- Ziegler et al^6^ compared 400, 600, and 800 IU/d from 2 to 9 months and found no significant differences in CTX at 4, 5.5, 7.5, and 9 months
- Gallo et al^2^ compared dosages of 400, 800, 1200, and 1600 IU/d from 1 to 12 months and found no significant differences in CTX at 36 months

Bone formation biomarkers:

- Holmlund-Suila et al^3^ compared dosages of 400, 1200, and 1600 IU/d from 2 weeks to 3 months and found no significant differences in PINP 3 months
- Ziegler et al^6^ compared 400, 600, and 800 IU/d from 2 to 9 months and found no significant differences in ALP or osteocalcin at 4, 5.5, 7.5, and 9 months

Although the evidence had strong consistency, the analyses were heterogeneous. The studies assessed different biomarkers of bone formation (i.e., PINP, ALP, and osteocalcin). The studies assessed the same biomarker of bone resorption (i.e., CTX); however, it was assessed at different ages (3, 4, 5.5, 7.5, 9, and 36 months), in relation to different periods of supplementation (2.5, 7, and 11 months), and during different phases of the study (within the supplementation period, at the end of the supplementation period, and 2 years after the supplementation period).

The evidence had limited precision; it is possible that the lack of statistical significance relates to insufficient statistical power. Two of the studies did not report power analyses,^3,6^ and the third study reported a power analysis related to BMD, but not CTX.^2^

The evidence has limited generalizability, as the participants in 2 of the 3 studies were predominantly^2^ or entirely^6^ White (the third study did not report race or ethnicity).

There was a moderate likelihood that the design and conduct of the studies prevented or minimized bias. The evidence was from randomized controlled trials, which had some risks of bias that varied between studies (Table 3).

Given this synthesis of the evidence, limited evidence suggests there is no relationship between consumption of 400 IU/d of vitamin D from supplements in infants younger than 12 months of age, compared with higher dosages of up to 1600 IU/d, and biomarkers of bone metabolism followed up to 36 months of age.

#### Comparisons of 400 IU/d with lower dosages of vitamin D

One of the 5 studies compared 400 IU/d with a lower dosage. Ziegler et al^6^ compared infants given 400 or 200 IU/d of vitamin D3 from 2 to 9 months of age. There were no significant differences in whole-body BMC or BMD at the end of winter (i.e., 5.5-9 months). There were also no significant differences in alkaline phosphatase, osteocalcin, and CTX at 4, 5.5, 7.5, and 9 months.

This is insufficient evidence to determine the relationship between 400 IU/d of vitamin D from supplements, compared with lower dosages, and bone health.

#### Comparisons of 200 IU/d for different durations with a placebo

One of the 5 studies compared 200 IU for different durations (i.e., birth to 6 months and 2 to 6 months) with a placebo. Ponnapakkam et al^4^ found no significant differences in ALP at 2, 4, and 6 months, and no cases of rickets in any of the participants.

This is insufficient evidence to determine the relationship between vitamin D from supplements, compared with no vitamin D from supplements, and bone health.

Table 2 Evidence examining the relationship between vitamin D from supplements consumed during infancy and toddlerhood and bone health^*^

Article, Year; Study design; Country | Vitamin D from supplements intervention vs comparator^†^ | Bone health outcomes | Significant findings | Nonsignificant findings
Gallo 2013 ^1^; RCT; Canada | 400 IU/d vitamin D3 from 1 mo to 12 mo vs; 800 IU/d vitamin D3 from 1 mo to 12 mo vs; 1200 IU/d vitamin D3 from 1 mo to 12 mo vs; 1600 IU/d vitamin D3 from 1 mo to 12 mo | Lumbar spine
Gallo 2013 ^1^; RCT; Canada | 400 IU/d vitamin D3 from 1 mo to 12 mo vs; 800 IU/d vitamin D3 from 1 mo to 12 mo vs; 1200 IU/d vitamin D3 from 1 mo to 12 mo vs; 1600 IU/d vitamin D3 from 1 mo to 12 mo | BMC (mean, g)
Gallo 2013 ^1^; RCT; Canada | 400 IU/d vitamin D3 from 1 mo to 12 mo vs; 800 IU/d vitamin D3 from 1 mo to 12 mo vs; 1200 IU/d vitamin D3 from 1 mo to 12 mo vs; 1600 IU/d vitamin D3 from 1 mo to 12 mo | @ 3 mo (N=NR) | | ~3 for all groups; NS
| | @ 6 mo (N=NR) | | ~3.5 for all groups; NS
| | @ 9 mo (N=NR) | | ~4.5 for all groups; NS
| | @ 12 mo (N=NR) | | ~5.5 for all groups; NS
| | Change in BMC (mean, g/mo)
| | 1 to 3 mo (N=NR) | | ~0.0-0.2 for all groups; NS
| | 3 to 6 mo (N=NR) | | ~0.2 for all groups; NS
| | 6 to 9 mo (N=NR) | | ~0.3 for all groups; NS
| | 9 to 12 mo (N=NR) | | ~0.3 for all groups; NS
| | Femur
| | BMC (mean, g)
| | @ 3 mo (N=NR) | | ~4.5-5 for all groups; NS
| | @ 6 mo (N=NR) | | ~6-7 for all groups; NS
| | @ 9 mo (N=NR) | | ~7-9 for all groups; NS
| | @ 12 mo (N=NR) | | ~9.5-11.5 for all groups; NS
| | Change in BMC (mean, g/mo)
| | 1 to 3 mo (N=NR) | | ~0.5-0.7 for all groups; NS
| | 3 to 6 mo (N=NR) | | ~0.5 for all groups; NS
| | 6 to 9 mo (N=NR) | | ~0.5-0.7 for all groups; NS
| | 9 to 12 mo (N=NR) | | ~0.5-1.3 for all groups; NS
| | Whole-body
| | BMC (mean, g)
| | @ 3 mo (N=NR) | | ~130-140 for all groups; NS
| | @ 6 mo (N=NR) | | ~160-180 for all groups; NS
| | @ 9 mo (N=NR) | | ~200 for all groups; NS
| | @ 12 mo (N=NR) | | ~230-250 for all groups; NS
| | Change in BMC (mean, g/mo)
| | 1 to 3 mo (N=NR) | | ~15-18 for all groups; NS
| | 3 to 6 mo (N=NR) | | ~12-15 for all groups; NS
| | 6 to 9 mo (N=NR) | | ~7-12 for all groups; NS
| | 9 to 12 mo (N=NR) | | ~7-12 for all groups; NS
Gallo 2016 ^2^; RCT; Canada | 400 IU/d vitamin D3 from 1 mo to 12 mo vs; 800 IU/d vitamin D3 from 1 mo to 12 mo vs; 1200 IU/d vitamin D3 from 1 mo to 12 mo vs; 1600 IU/d vitamin D3 from 1 mo to 12 mo | Lumbar spine, vertebrae L1–L4
Gallo 2016 ^2^; RCT; Canada | 400 IU/d vitamin D3 from 1 mo to 12 mo vs; 800 IU/d vitamin D3 from 1 mo to 12 mo vs; 1200 IU/d vitamin D3 from 1 mo to 12 mo vs; 1600 IU/d vitamin D3 from 1 mo to 12 mo | BMC (mean [95% CI], g) @ 36 mo (N=25, 24, 25, 11) | | 11.5 [10.8, 12.2] vs; 11.4 [10.8, 12.0] vs; 11.8 [11.3, 12.3] vs; 11.6 [10.3, 12.9];; p=0.865
| | BMD (mean [95% CI], g/cm2) @ 36 mo (N=25, 24, 25, 11) | | 0.474 [0.450, 0.500] vs; 0.463 [0.445, 0.481] vs; 0.479 [0.462, 0.496] vs; 0.463 [0.429, 0.498];; p=0.655
| | BMD Z-score (mean [95% CI]) @ 36 mo (N=25, 24, 25, 11) | | 0.46 [0.05, 0.97] vs; 0.18 [−0.22, 0.59] vs; 0.62 [0.25, 0.98] vs; -0.18 [-0.56, 0.92];; p=0.457
| | Change in BMC (mean [95% CI], g)
| | from 12 to 36 mo (N=24, 24, 24, 11) | | 5.71 [4.96, 6.47] vs; 5.74 [4.55, 6.93] vs; 6.13 [5.61, 6.65] vs; 5.89 [4.84, 6.95];; p=0.882
| | from 1 to 36 mo (N=25, 24, 25, 11) | | 8.48 [7.82, 9.14] vs; 8.83 [8.29, 9.37] vs; 9.00 [8.36, 9.65] vs; 8.62 [7.47, 9.76];; p=0.652
| | Whole body
| | BMC (mean [95% CI], g) @ 36 mo (N=24, 23, 25, 10) | | 600.6 [578.9, 622.3] vs; 593.1[575.4, 610.7] vs; 593.1 [576.5, 609.6] vs; 633.1 [591.5, 674.9];; p=0.110
| | BMD (mean [95% CI], g/cm^2^) @ 36 mo (N=24, 23, 25, 10) | | 0.622 [0.607, 0.637] vs; 0.626 [0.611, 0.642] vs; 0.618 [0.604, 0.633] vs; 0.651 [0.615, 0.686];; p=0.133
| | BMD Z-score (mean [95% CI]) @ 36 mo (N=24, 23, 25, 10) | | 2.00 [1.53, 2.47] vs; 1.97 [1.58, 2.36] vs; 1.83 [1.46, 2.19] vs; 2.61 [1.63, 3.59];; p=0.245
| | Change in BMC (mean [95% CI], g)
| | from 12 to 36 mo (N=18, 21, 21, 6) | | 354.2 [329.8, 378.6] vs; 362.10 [345.3, 378.9] vs; 361.7 [346.0, 377.5] vs; 388.7 [333.4, 444.1];; p=0.377
| | from 1 to 36 mo (N=24, 23, 25, 10) | | 497.0 [474.6, 519.5] vs; 496.6 [479.0, 514.2] vs; 493.5 [475.3, 511.8] vs; 534.0 [492.0, 576.0];; p=0.931
| | Plasma C-terminal telopeptide of type I collagen (CTX) (mean [95% CI], ng/mL) @ 36 mo (N= NR) | | 1.13 [1.06–1.20]; NS
Holmlund-Suila 2012 ^3^; RCT; Finland | 400 IU/d vitamin D3 from 2 wk to 3 mo vs; 1200 IU/d vitamin D3 from 2 wk to 3 mo vs; 1600 IU/d vitamin D3 from 2 wk to 3 mo | Total and trabecular bone
Holmlund-Suila 2012 ^3^; RCT; Finland | 400 IU/d vitamin D3 from 2 wk to 3 mo vs; 1200 IU/d vitamin D3 from 2 wk to 3 mo vs; 1600 IU/d vitamin D3 from 2 wk to 3 mo | BMD (mean ± SE, mg/cm^3^) @ 3 mo (N=25, 29, 28) | | 448 ± 13 vs; 430 ± 12 vs; 451 ± 12;; p=0.387
| | Cross sectional area (mean ± SE, mm^2^) @ 3 mo (N=25, 29, 28) | 72 ± 3 vs; 77 ± 3 vs; 81 ± 3^*^;; p=0.069; Cross sectional area (mm2) significantly higher in 1600 IU/d group than in 400 IU/d group (p=0.022)
| | Cortical bone
| | BMD (mean ± SE, mg/cm^3^) @ 3 mo (N=25, 29, 28) | | 724 ± 8 vs; 716 ± 7 vs; 726 ± 7;; p=0.609
| | Cross sectional area (mean ± SE, mm^2^) @ 3 mo (N=25, 29, 28) | 31 ± 1 vs; 32 ± 1 vs; 34 ± 1^*^;; p=0.053; Cross sectional area (mm2) significantly higher in 1600 IU/d group than 400 IU/d group (p=0.027) and 1200 IU/d group (p=0.050)
| | Polar stress and strain index (mean ± SE, mm^3^) @ 3 mo (N=25, 29, 28) | 48 ± 2 vs; 48 ± 2 vs; 54 ± 2^*^;; p=0.070; Polar stress and strain index (mm3) significantly higher in 1600 IU/d group than 400 IU/d group (p=0.043) and 1200 IU/d group (p=0.050)
| | Procollagen I N-terminal propeptide (PINP) (mean, μg/L) @ 3 mo (N=25, 29, 28) | | 2.2 vs 2.1 vs 2.0; p=0.992
| | C-terminal cross-linked telopeptides of type I collagen (mean, μg/L) @ 3 mo (N=25, 29, 28) | | 1.4 vs 1.4 vs 1.3; p=0.757
Ponnapakkam 2010 ^4^; RCT; United States | 200 IU/d vitamin D3 from birth to 6 mo vs; 200 IU/d vitamin D3 from 2 mo to 6 mo vs; placebo from birth to 6 mo | Serum alkaline phosphatase (mean ± SE, IU/L)
Ponnapakkam 2010 ^4^; RCT; United States | 200 IU/d vitamin D3 from birth to 6 mo vs; 200 IU/d vitamin D3 from 2 mo to 6 mo vs; placebo from birth to 6 mo | @ 2 mo (N=33) | | ~135 ± 15 vs; ~137 ± 15 vs; ~125 ± 10; NS
| | @ 4 mo (N=22) | | ~137 ± 25 vs; ~100 ± 10 vs; ~120 ± 15; NS
| | @ 6 mo (N=25) | | ~140 ± 20 vs; ~100 ± 15 vs; ~80 ± 10; NS
| | Incidence of rickets
| | @ 2 mo (N=NR) | | No infants with rickets; NS
| | @ 4 mo (N=NR) | | No infants with rickets; NS
| | @ 6 mo (N=NR) | | No infants with rickets; NS
Rosendahl, 2018 ^5^; RCT; Finland | 400 IU/d vitamin D3 from 2 wk to 24 mo vs; 1200 IU/d vitamin D3 from 2 wk to 24 mo | Total bone
Rosendahl, 2018 ^5^; RCT; Finland | 400 IU/d vitamin D3 from 2 wk to 24 mo vs; 1200 IU/d vitamin D3 from 2 wk to 24 mo | BMC (mean difference [95% CI], mg/mm) @ 24 mo (N=343, 361) | | 0.4 [−0.8, 1.6]; NS
| | BMD (mean difference [95% CI], mg/cm3) @ 24 mo (N=343, 361) | . | 2.9 [−8.3, 14.2]; NS
| | Cross sectional area (mean difference [95% CI], mm2) @ 24 mo (N=343, 361) | . | −0.9 [−5.0, 3.2]; NS
| | Polar moment of inertia (mean difference [95% CI], mm4) @ 24 mo (N=343, 361) | | −66.0 [−274.3, 142.3]; NS
| | Cortical bone
| | BMC (mean difference [95% CI], mg/mm) @ 24 mo (N=343, 361) | | 1.0 [−0.4, 2.4]; NS
| | BMD (mean difference [95% CI], mg/cm^3^) @ 24 mo (N=343, 361) | . | 6.0 [−3.2, 15.2]; NS
| | Cross sectional area (mean difference [95% CI], mm^2^) @ 24 mo (N=343, 361) | . | 1.0 [−0.4, 2.4]; NS
| | Polar moment of inertia (mean difference [95% CI], mm^4^) @ 24 mo (N=343, 361) | | 9.9 [−69.1, 88.9]; NS
Ziegler 2017 ^6^; RCT; United States | 200 IU/d vitamin D3 from 2 mo to 9 mo vs; 400 IU/d vitamin D3 from 2 mo to 9 mo vs; 600 IU/d vitamin D3 from 2 mo to 9 mo vs; 800 IU/d vitamin D3 from 2 mo to 9 mo | Bone-specific alkaline phosphatase (mean ± SD, IU/L)
Ziegler 2017 ^6^; RCT; United States | 200 IU/d vitamin D3 from 2 mo to 9 mo vs; 400 IU/d vitamin D3 from 2 mo to 9 mo vs; 600 IU/d vitamin D3 from 2 mo to 9 mo vs; 800 IU/d vitamin D3 from 2 mo to 9 mo | @ 4 mo (N=46, 44, 42, 33) | | 167 ± 42 vs; 188 ± 51 vs; 168 ± 41 vs; 194 ± 56^‡^; NS
| | @ 5.5 mo (N=NR) | | 145 ± 40 vs; 158 ± 41 vs; 133 ± 33 vs; 161 ± 42^‡^; NS
| | @ 7.5 mo (N=NR) | | 123 ± 31 vs; 140 ± 40 vs; 122 ± 38 vs; 159 ± 46^‡^; NS
| | @ 9 mo (N=NR) | | 141 ± 52 vs; 160 ± 68 vs; 128 ± 40 vs; 170 ± 49^‡^; NS
| | Osteocalcin (mean ± SD, mcg/L)
| | @ 4 mo (N=46, 44, 42, 33) | | 16.8 ± 4 vs; 17.4 ± 6.5 vs; 18.7 ± 6.0 vs; 16.8 ± 5.4; NS
| | @ 5.5 mo (N=NR) | | 16.7 ± 4 vs; 15.3 ± 6.3 vs; 17.2 ± 5.6 vs; 14.4 ± 4.3; NS
| | @ 7.5 mo (N=NR) | | 19.7 ± 5 vs; 18.5 ± 6.6 vs; 20.5 ± 7.7 vs; 17.0 ± 7.0; NS
| | @ 9 mo (N=NR) | | 23.0 ± 6 vs; 22.4 ± 6.8 vs; 24.8 ± 6.7 vs; 19.3 ± 8.4; NS
| | C-terminal telopeptides (mean ± SD, mcg/L)
| | @ 4 mo (N=45, 43, 42, 30) | | 1.21 ± 0.30 vs; 1.23 ± 0.26 vs; 1.21 ± 0.36 vs; 1.32 ± 0.31; NS
| | @ 5.5 mo (N=NR) | | 1.16 ± 0.25 vs; 1.15 ± 0.28 vs; 1.20 ± 0.31 vs; 1.21 ± 0.28; NS
| | @ 7.5 mo (N=NR) | | 1.13 ± 0.27 vs; 1.12 ± 0.27 vs; 1.22 ± 0.39 vs; 1.16 ± 0.37; NS
| | @ 9 mo (N=NR) | | 1.25 ± 0.25 vs; 1.18 ± 0.26 vs; 1.30 ± 0.33 vs; 1.13 ± 0.28; NS
| | Whole-body BMC (mean ± SD, g) @ the end of winter (i.e., 5.5-9 mo); (N=17, 17, 14, 11) | 168.5 ± 20.3 vs; 184.7 ± 36.6 vs; 166.6 ± 21.9^*^ vs; 171.2 ± 25.4;; BMC (g) significantly lower in 600 IU/d group than 200 IU/d and 400 IU/d groups, p <0.05
| | in the subsample of infants who were 5.5 mo at the end of winter; (N=6, 7, 8, 3) | 159.4 ± 20.1 vs; 161.9 ± 28.0 vs; 157.6 ± 18.7^*^ vs; 144.7 ± 29.3;; BMC (g) significantly lower in 600 IU/d group than 200 IU/d group, p<0.05
| | in the subsample of infants who were 7.5 mo at the end of winter; (N=10, 4, 4, 4) | | 172.6 ± 20.4 vs; 183.2 ± 16.5 vs; 175.8 ± 26.1 vs; 182.1 ± 10.3; NS
| | in the subsample of infants who were 9 mo at the end of winter; (N=1, 6, 2, 4) | | 181.3 ± NR vs; 212.3 ± 39.5 vs; 184.3 ± 12.1 vs; 180.2 ± 22.7; NS
| | Whole-body BMC (mean ± SD, g/kg) @ the end of winter (i.e., 5.5-9 mo); (N=17, 17, 14, 11) | 22.37 ± 1.47 vs; 22.56 ± 1.61 vs; 21.02 ± 1.54^*^ vs; 22.00 ± 1.48;; BMC (g/kg) significantly lower in 600 IU/d group than 200 IU/d and 400 IU/d groups, p <0.05
| | in the subsample of infants who were 5.5 mo at the end of winter; (N=6, 7, 8, 3) | 22.17 ± 1.58 vs; 21.61 ± 1.50 vs; 20.30 ± 1.47^*^ vs; 20.75 ± 1.19;; BMC (g/kg) significantly lower in 600 IU/d group than 200 IU/d group, p<0.05
| | in the subsample of infants who were 7.5 mo at the end of winter; (N=10, 4. 4, 4) | | 22.41 ± 1.53 vs; 22.97 ± 0.62 vs; 21.98 ± 1.39 vs; 21.93 ± 1.65; NS
| | in the subsample of infants who were 9 mo at the end of winter; (N=1, 6, 2, 4) | | 23.17 ± NR vs; 23.38 ± 1.77 vs; 22.00 ± 0.13 vs; 23.00 ± 0.867; NS
| | Whole-body BMD (mean ± SD, g/cm^2^) @ the end of winter (i.e., 5.5-9 mo); (N=17, 17, 14, 11) | 0.2688 ± 0.0193 vs; 0.2768 ± 0.0311 vs; 0.2516 ± 0.0326^*^ vs; 0.2668 ± 0.021;; BMD (g/cm2) significantly lower in 600 IU/d group than 200 IU/d and 400 IU/d groups, p <0.05
| | in the subsample of infants who were 5.5 mo at the end of winter; (N=6, 7, 8, 3) | | 0.2645 ± 0.0217 vs; 0.2586 ± 0.0287 vs; 0.2491 ± .0289 vs; 0.2477 ± 0.0136; NS
| | in the subsample of infants who were 7.5 mo at the end of winter; (N=10, 4, 4, 4) | | 0.2709 ± 0.0196 vs; 0.2847 ± 0.0177 vs; 0.2475 ± 0.0489 vs; 0.2732 ± 0.0180; NS
| | in the subsample of infants who were 9.0 mo at the end of winter; (N=1, 6, 2, 4) | | 0.2730 ± NR vs; 0.2933 ± 0.0329 vs; 0.2695 ± 0.0064 vs; 0.2755 ± 0.0236; NS

* Abbreviations: BMC – bone mineral content, BMD – bone mineral density, CI – confidence interval, CTX – C terminal telopeptide of type I collagen, IU – International units, L1 –- lumbar spine vertebra 1, L4 – lumbar spine vertebra 4, NR – not reported, NS – nonsignificant, PINP – procollagen I N-terminal propeptide, RCT – randomized controlled trial, SD – standard deviation, SE – standard error

† Interventions and comparators, from the articles included in the body of evidence, which compare vitamin D from supplements with different dosages of vitamin D from supplements or a placebo.

‡ Study authors state “Bone-specific alkaline phosphatase showed a very modest yet statistically significant (p<0.01) increase with the highest dose of VD (800 IU/day)” however, the results reported in the table are not marked as statistically significant.

Table 3 Risk of bias for randomized controlled trials examining consumption of vitamin D from supplements during infancy and toddlerhood and bone health^*^,^†^

| Randomization | Identification of participants - randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
Gallo, 2013^1^ | Low | Low | Low | Some Concerns | Low | Low
Gallo, 2016^2^ | Low | Low | Some Concerns | Some Concerns | Low | Some Concerns
Holmlund-Suila, 2012^3^ | Low | Low | Low | Low | Some Concerns | Low
Ponnapakkam, 2010^4^ | High | High | High | High | High | High
Rosendahl, 2018^5^ | Low | Low | Low | Low | Low | Low
Ziegler, 2017^6^ | Some Concerns | Low | High | High | Low | High

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

### Research recommendations

Investigate how much (if any) vitamin D supplementation is needed for bone health under the following circumstances:

a) When the mother is taking high doses of vitamin D, and
b) When the infant has short periods of sun exposure in certain latitudes.

Future studies should be appropriately powered, include racially and ethnically diverse samples, and report baseline vitamin D status, human milk vitamin D content, and sun exposure.

### Included articles

1 Gallo S, Comeau K, Vanstone C, . Effect of different dosages of oral vitamin D supplementation on vitamin D status in healthy, breastfed infants: a randomized trial. JAMA. 2013;309(17):1785–1792.doi: 10.1001/jama.2013.3404.23632722
2 Gallo S, Hazell T, Vanstone CA, . Vitamin D supplementation in breastfed infants from Montreal, Canada: 25-hydroxyvitamin D and bone health effects from a follow-up study at 3 years of age. Osteoporos Int. 2016;27(8):2459–2466.doi: 10.1007/s00198-016-3549-z.26968165
3 Holmlund-Suila E, Viljakainen H, Hytinantti T, Lamberg-Allardt C, Andersson S, Makitie O. High-dose vitamin d intervention in infants--effects on vitamin d status, calcium homeostasis, and bone strength. J Clin Endocrinol Metab. 2012;97(11):4139–4147.doi: 10.1210/jc.2012-1575.22933541
4 Ponnapakkam T, Bradford E, Gensure R. A treatment trial of vitamin D supplementation in breast-fed infants: universal supplementation is not necessary for rickets prevention in Southern Louisiana. Clin Pediatr (Phila). 2010;49(11):1053–1060.doi: 10.1177/0009922810376320.20724336
5 Rosendahl J, Valkama S, Holmlund-Suila E, . Effect of Higher vs Standard Dosage of Vitamin D3 Supplementation on Bone Strength and Infection in Healthy Infants: A Randomized Clinical Trial. JAMA Pediatr. 2018;172(7):646–654.doi: 10.1001/jamapediatrics.2018.0602.29813149
6 Ziegler EE, Koo WW, Nelson SE, Jeter JM. Lack of Effect of Graded Doses of Vitamin D on Bone Metabolism of Breastfed Infants. J Clin Nutr Metab. 2017;1(1).doi.

ii National Institutes of Health Office of Dietary Supplements. Dietary Supplement Health and Education Act of 1994 Public Law 103-417 103rd Congress: Sec. 3. Definitions. https://ods.od.nih.gov/About/DSHEA_Wording.aspx#sec3 Published October 25, 1994. Accessed May 18, 2020

iii Golden NH, Abrams SA. Optimizing bone health in children and adolescents. Pediatrics. 2014;134(4):e1229–1243. doi:10.1542/peds.2014-2173.25266429

iv A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

v Institute of Medicine. Dietary Reference Intakes for Calcium and Vitamin D. Washington, DC: The National Academies Press;2011. doi:10.17226/13050.978-0-309-16394-1.

vi Golden NH, Abrams SA. Optimizing bone health in children and adolescents. Pediatrics. 2014;134(4):e1229–1243. doi:10.1542/peds.2014-2173.25266429