# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CDC: Centers for Disease Control and Prevention
CNPP: Center for Nutrition Policy and Promotion
FDA: U.S. Food and Drug Administration
FNS: USDA Food and Nutrition Service
HHS: U.S. Department of Health and Human Services
IOTF: International Obesity Task Force
NESR: Nutrition Evidence Systematic Review
NHANES: National Health and Nutrition Examination Survey
NIH: National Institutes of Health
ONGA: Office of Nutrition Guidance and Analysis
SES: Socio-economic status
USDA: U.S. Department of Agriculture
WIC: Supplemental Nutrition Program for Women, Infants and Children
WFL: Weight-for-length
WHO: World Health Organization