# WHAT IS THE RELATIONSHIP BETWEEN THE DURATION, FREQUENCY, AND VOLUME OF EXCLUSIVE HUMAN MILK AND/OR INFANT FORMULA CONSUMPTION AND OVERWEIGHT AND OBESITY?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and overweight and obesity?

### What is the answer to the question?

- Moderate evidence from observational studies indicates that ever, compared with never, consuming human milk is associated with lower risk of overweight and obesity at 2 years of age and older, particularly if the duration of human milk consumption is 6 months or longer.
- Insufficient evidence is available to determine the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and obesity at 2 years of age and older; the available evidence was inconsistent.
- Insufficient evidence is available to determine the relationship between the duration of exclusive human milk consumption prior to the introduction of infant formula and overweight and obesity at 2 years of age and older.
- No evidence is available to determine the relationship between the intensity, proportion, or amount of human milk consumed by mixed-fed infants and overweight and obesity at 2 years of age and older.
- No evidence is available to determine the relationship between the intensity, proportion, or amount of human milk consumed at the breast vs by bottle in infants fed human milk as their only source of milk and overweight and obesity at 2 years of age and older.
- No evidence is available to determine the relationship between consuming human milk or infant formula (i.e., a single substance) vs human milk and infant formula (i.e., both substances, e.g., “topping up”) during a single feeding session and overweight and obesity at 2 years of age and older.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- The systematic review studied 2 different populations. The first was generally healthy infants and toddlers (birth to 24 months) who were fed human milk and/or infant formula and who had overweight and obesity outcomes examined at 2 years of age or older. The second was generally healthy siblings who were fed differently during infancy or who had different outcomes, or both, and who had rapid weight gain examined between birth and 24 months and/or BMI, body composition, overweight or obesity examined at 2 years of age or older.

### What evidence was found?

- This review includes 42 articles.
- The review examined available evidence about:
  ○ Infants who ever consumed milk (i.e., any amount of human milk) compared with infants who never consumed human milk,
  ○ Infants who consumed human milk (i.e., any amount of human milk) for different durations,
  ○ Infants who consumed human milk exclusively for different durations before infant formula was added to their diets, and
  ○ Mixed-fed infants (i.e., consuming both human milk and infant formula, but not complementary foods and beverages) who consumed different amounts of human milk.
  ○ Infants who consumed human milk as their only source of milk and who consumed different intensities, proportions, or amounts of human milk at the breast versus by bottle, and
  ○ Mixed-fed infants who consumed a single substance at a single feeding session (i.e., either human milk or infant formula) with mixed-fed infants who consumed both substances at a single feeding session (e.g., “topping up”).
- These articles examined available evidence related to overweight and obesity at 2 years of age and older and, for siblings, about rapid weight gain from birth to 24 months, BMI, and body composition at 2 years of age and older.
- Most evidence examined overweight and obesity in infants who ever consumed human milk compared to infants who never consumed human milk, or in infants who consumed human milk for different durations.
  ○ Infants who ever consume human milk, and especially infants who consume human milk for 6 months or longer, may have lower risk of overweight and obesity throughout life than infants who never consume human milk. The findings may be due, in part, to factors other than infant feeding that also impact overweight and obesity.
  ○ It is not clear whether infants who consume human milk for different durations have different risk of overweight and obesity at 2 years of age and older. The evidence was inconsistent.
- There was not a lot of evidence about infants who consumed human milk exclusively for different durations before infant formula was added to their diets. There was no evidence about infants who consumed human milk at the breast compared to by bottle, or about mixed-fed infants who consumed different amounts of human milk or who consumed human milk and infant formula during the same feeding session compared to during different feeding sessions.

### How up-to-date is this systematic review?

- This review searched for studies published between January 2011 and September 2019 and additional sibling studies published between January 1980 and September 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and overweight and obesity?

### Conclusion statements and grades

#### Ever vs never consuming human milk

Moderate evidence from observational studies indicates that ever, compared with never, consuming human milk is associated with lower risk of overweight and obesity at age 2 years and older, particularly if the duration of human milk consumption is 6 months or longer. (Grade: Moderate)

#### Duration of any human milk consumption among infants fed human milk

Insufficient evidence is available to determine the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and obesity at age 2 years and older; the available evidence was inconsistent. (Grade: Grade not assignable)

#### Duration of exclusive human milk consumption before the introduction of infant formula

Insufficient evidence is available to determine the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and overweight and obesity at age 2 years and older. (Grade: Grade not assignable)

#### Intensity, proportion, or amount of human milk consumed by mixed-fed infants

No evidence is available to determine the relationship between the intensity, proportion, or amount of human milk consumed by mixed-fed infants and overweight and obesity at age 2 years and older. (Grade: Grade not assignable)

#### Intensity, proportion, or amount of human milk consumed at the breast vs by bottle in infants fed human milk as their only source of milk

No evidence is available to determine the relationship between the intensity, proportion, or amount of human milk consumed at the breast vs by bottle in infants fed human milk as their only source of milk and overweight and obesity at age 2 years and older. (Grade: Grade not assignable)

#### Consuming human milk or infant formula (i.e., a single substance) vs human milk and infant formula (i.e., both substances) during a single feeding session

No evidence is available to determine the relationship between consuming human milk or infant formula (i.e., a single substance) vs human milk and infant formula (i.e., both substances, e.g., “topping up”) during a single feeding session and overweight and obesity at age 2 years and older. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review examined the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and overweight and obesity. Specifically, this systematic review examined available evidence that compared:
  ○ Infants who ever consumed milk (i.e., any amount of human milk) with infants who never consumed human milk,
  ○ Infants who consumed human milk (i.e., any amount of human milk) for different durations,
  ○ Infants who consumed human milk exclusively for different durations before the introduction of infant formula,
  ○ Mixed-fed infants (i.e., consuming both human milk and infant formula, but not complementary foods and beverages) who consumed different intensities, proportions, or amounts of human milk,
  ○ Infants who consumed human milk as their only source of milk and who consumed different intensities, proportions, or amounts of human milk at the breast versus by bottle, and
  ○ Mixed-fed infants who consumed a single substance at a single feeding session (i.e., either human milk or infant formula) with mixed-fed infants who consumed both substances at a single feeding session (e.g., “topping up”).
- Human milk refers to mother’s own milk provided at the breast (i.e., nursing) or expressed and fed fresh or after refrigeration or freezing. Examinations of donor milk are not included in this review. Exclusive human milk consumption refers to consuming human milk alone and not in combination with infant formula or complementary foods and beverages. Infant formula refers to commercially prepared infant formula meeting the FDA and/or Codex Alimentarius international food standards. Complementary foods and beverages are foods and beverages other than human milk or infant formula (liquids, semisolids, and solids) provided to an infant or young child to provide nutrients and energy.
- The outcomes of interest were overweight and obesity at ages 2 years and older. Available evidence about rapid weight gain from birth to 24 months and BMI and body composition at ages 2 years and older were also examined from studies that conducted within-famliy analyses of discordant siblings (i.e., siblings fed differently during infancy, siblings with differences in outcome status, or both).
- This review identified 42 articles that met the inclusion criteria.^1–42^ Thirty of the 42 articles presented evidence about ever, compared with never, consuming human milk, and 21 of the 42 articles presented evidence about different durations of any human milk consumption (i.e. some articles presented evidence about both exposures).
- The 30 articles that examined the relationship between ever, compared with never, consuming human milk, and overweight and/or obesity at ages 2 years and older presented evidence from 21 independent cohorts.
  ○ The evidence had strong consistency. Fourteen of the 21 studies found significant associations and all of them showed that ever, compared with never, consuming human milk is associated with lower risk of overweight and/or obesity at ages 2 years and older. One study showed a marginal association in the same direction, and some of the remaining studies were underpowered.
  ○ The evidence available from 5 of 7 studies that compared infants who consumed human milk for different durations with infants who never consumed human milk suggested that a longer duration of human milk consumption (e.g., ≥6 months) is most likely to be associated with reduced risk of overweight or obesity, compared to never consuming human milk.
  ○ In 4 studies, the investigators conducted within-family analyses of siblings, which are designed to reduce bias due to confounding from genetic and environmental factors (factors that siblings share). Some of these analyses showed an attenuation of the significant associations found in full-sample analyses, suggesting that confounding may explain some of the association between ever, compared with never, consuming human milk and overweight and/or obesity at ages 2 years and older.
  ○ The ability to draw stronger conclusions was primarily limited by the potential for confounding in a body of evidence made up of observational studies, and some concerns about the generalizability of the evidence from the studies conducted outside the United States (because U.S. populations may have higher risk of overweight and obesity than do the populations sampled for the non-U.S. studies).
- The 21 articles that examined the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity at ages 2 years and older presented evidence from 1 cluster randomized controlled trial and 18 independent cohorts.
  ○ The evidence was inconclusive. Nine of the 19 studies reported significant associations, but they were inconsistent in direction. In addition, potential bias from confounding and the limited generalizability of the evidence from the non-U.S. studies raised concerns (in particular because the prevalence of obesity among the participants of the cluster randomized controlled trial, conducted in Belarus, was much lower than the prevalence among youth in the United States).
- Evidence available from 2 studies was insufficient to determine the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and overweight and/or obesity at ages 2 years and older.
- No studies were identified that examined the intensity, proportion, or amount of human milk consumed by mixed-fed infants, the intensity, proportion, or amount of human milk consumed at the breast versus by bottle, or consuming a single substance (i.e., either human milk or infant formula) versus both human milk and infant formula during a single feeding session.

### Ever, compared with never, consuming human milk

#### Description of the evidence examining the relationship between ever, compared with never, consuming human milk and body composition, including obesity, from studies that conducted within-family comparisons of siblings (Table 1)

Six articles, published between 2003 and 2019, conducted within-family analyses that compared siblings who ever and never consumed human milk and their BMI or overweight and/or obesity status.^3,6,10,14,27,32^ These articles presented evidence from 4 independent U.S. cohorts, which are described below.

1. Linked CENTURY Study
  Hawkins et al^14^ examined a sample of singleton children from the Linked CENTURY Study in the United States. Participants were from an existing clinical database of well-child visits at Atrius Health in Eastern Massachusetts. The authors examined initiation of human milk feeding as a dichotomous variable, which was obtained from hospital records at birth. Height and weight were measured by medical assistants at 2 and 5 years of age. The outcomes of interest were BMI z-score as a continuous variable and obesity (i.e., BMI ≥95^th^ percentile) as a dichotomous variable (both based on CDC growth curves). The authors conducted analyses in the full sample (N=55,058 at 2 years and 43,893 at 5 years), in a subsample consisting of siblings (N=21,455 at 2 years and 17,083 at 5 years) and in a subsample of siblings with discordant outcomes (N= 2260 at 2 years and 3249 at 5 years).
  - In the full sample, initiating, compared with not initiating, human milk feeding was associated with a significantly lower BMI z-score at 2 and at 5 years of age (β [95% CI] = −0.06 [−0.09, −0.04] and −0.09 [−0.11, −0.07], respectively). In the subsample of families with more than 1 sibling, the associations were nearly identical (β [95% CI] = −0.06 [−0.10, −0.02] and −0.09 [−0.13, −0.06]). In the subsample of siblings with discordant outcomes, initiating human milk feeding was associated with a significantly lower BMI z-score at 5 years of age (β = −0.07 [95% CI −0.13, −0.01]; the association at 2 years of age was in the same direction but lacked statistical significance (β = −0.04 [95% CI −0.10, 0.03]).
  - In the full sample, initiating, compared with not initiating, human milk feeding was associated with significantly lower odds of obesity at both 2 and 5 years of age (OR [95% CI] = 0.80 [0.73, 0.87] and 0.77 [0.72, 0.83], respectively). In the subsample of families with more than 1 sibling, the odds were the same with slightly wider confidence intervals (OR [95% CI] = 0.80 [0.69, 0.92] and 0.77 [0.69, 0.87], respectively). In the subsample of siblings with discordant outcomes, initiating human milk feeding was not significantly associated with obesity at 2 or 5 years of age, and the odds ratios were closer to the null (OR [95% CI] = 0.97 [0.72, 1.32] and 0.94 [0.74, 1.20], respectively).
2. Children of the National Longitudinal Survey on Youth 1979 Cohort (Children of NLSY79)
  Two articles^3,6^ examined samples of singleton children and adolescents whose mothers were part of the NLSY79 cohort from the United States. Anderson et al (2003)^3^ examined offspring who were 3 to 11 years of age between 1986 and 1996, whereas Colen and Ramey^6^ examined offspring who were 4 to 14 years of age between 1986 and 2010 and born after the year 1978. Colen and Ramey^6^ reported that about 75% of participants were non-Hispanic white.
  Both articles examined ever versus never consuming human milk as a dichotomous variable. Infant-feeding data were obtained by maternal report at biannual survey rounds starting in 1986.
  Both articles used height and weight data, which were measured for most participants (i.e., in the article by Anderson et al (2003),^3^ 15% of children’s height and 22% of children’s weight were reported by mothers and in the article by Colen and Ramey,^6^ approximately 36% of child and adolescent height and weight data were reported by mothers or participants). Both articles examined obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) as a dichotomous variable, and Colen and Ramey^6^ also examined BMI as a continuous variable.
  Anderson et al (2003)^3^ conducted analyses on the full sample (N=16,650 observations using a probit model and N=15,050 observations using an instrumental variable model), and on subsamples of siblings measured at the same point in time (mean 5.9 and 9.2 years of age for the younger and older siblings, respectively; N=7919 observations), and at the same age (mean age of 6.6 years; N=4471 observations).
  - In the full sample, children who were ever fed human milk had an approximately 1.8% decrease in the likelihood of being obese relative to children never fed human milk at 3 to 11 years of age (β = −0.018 ± 0.008 and −0.016 ± 0.010, from probit and instrumental variable models, respectively; p-values were not reported, but the instrumental variable model was described as non-signficant).
  - In both sibling subsamples (i.e., with outcomes measured at the same age and at the same time point), being fed human milk was not significantly associated with the likelihood of being obese at 3 to 11 years of age (β = −0.021 ± 0.023 and 0.012 ± 0.017, respectively).
  Colen and Ramey^6^ conducted analyses on the full sample (N=8237 participants), on a subsample of siblings (N=7319 participants), and on a second subsample of siblings with discordant infant feeding (i.e., siblings fed differently during infancy; N=1773 participants).
  - In the full sample and sibling subsample, ever compared with never consuming human milk was associated with a significantly lower BMI at 4 to 14 years of age (β = −0.449 ± 0.094 and −0.413 ± 0.101, respectively; p<0.001 for both). In the discordant sibling subsample, the association was in the same direction but was smaller and lacked statistical significance (β = −0.141 ± 0.101).
  - Likewise, in the full sample and sibling subsample, ever compared with never consuming human milk was associated with a significantly lower log odds of obesity at 4 to 14 years of age (β = −0.342 ± 0.066 and −0.369 ± 0.074, respectively; p<0.001 for both). In the discordant sibling subsample, the association was in the same direction but was smaller and lacked statistical significance (β = −0.173 ± 0.164).
3. National Longitudinal Study of Adolescent Health (Add Health)
  Two articles^10,32^ presented evidence from the Add Health study from the United States. This cohort is a nationally representative sample of 10- to 18-year-olds in grades 7 to 12 during the 1994-1995 school year (baseline). Low-income, African-American, and Hispanic youth were oversampled. Nelson et al^32^ excluded members of the cohort if they had severe disabilities or pregnancies, were Native Americans, or had graduated from high school, and reported that the sample was 72% non-Hispanic white, 13% non-Hispanic black, 11% Hispanic and 3% Asian.
  Both articles examined ever versus never consuming human milk as a dichotomous variable. In addition, Nelson et al^32^ examined dichotomous comparisons of participants who were never fed human milk with participants who were fed human milk for different durations (i.e., ≥3 months, <3 months, 3-5.99 months, 6-8.99 months and ≥9 months). Infant-feeding data were obtained by parent recall at 10 to 18 years (i.e., baseline).
  Evenhouse and Reilly^10^ examined BMI as a continuous variable and overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) and obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) as dichotomous variables at baseline (i.e., 10 to 18 years of age). Nelson et al^32^ examined BMI z-score (based on CDC growth curves) as a continuous variable and overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) as a dichotomous variable at 12 to 21 years of age. Neither of the articles reported the methods for anthropometric data collection.
  Evenhouse and Reilly^10^ conducted analyses on the full sample (N=16,903), on a subsample of siblings (N=3773) and on a second subsample of siblings with discordant infant feeding (i.e., sibships in which 1 sibling was ever fed human milk and the other was never fed human milk; N=576).
  - In the full sample, the sibling subsample, and the discordant sibling subsample, ever compared with never consuming human milk was not significantly associated with BMI at 10 to 18 years of age (β = −0.141 ± 0.101, −0.34 ± 0.16, and 0.40 ± 0.33, respectively; p<0.10 for the full-sample and sibling-subsample analyses)
  - Likewise, in the full sample, the sibling subsample, and the discordant sibling subsample, ever compared with never consuming human milk was not significantly associated with odds of overweight/obesity (OR = 0.79 ± 0.03, 0.87 ± 0.08, 1.32 ± 0.21, respectively; p<0.10 for the full-sample and discordant-sibling subsample analyses), or obesity (OR = 0.77 ± 0.04, 0.88 ± 0.11, 1.17 ± 0.25, respectively; p<0.10 for the full-sample analysis) at 10 to 18 years of age.
  Nelson et al^32^ conducted analyses on the full sample stratified by sex (N=5929 males, 6069 females), on a subsample of siblings (N=1700), and on subsamples of siblings with discordant infant feeding and outcomes (i.e., in which the overweight sibling had been fed human milk and the non-overweight sibling had not, and in which the overweight sibling had not been fed human milk and the non-overweight sibling had; N=224 discordant siblings).
  - In the full sample, ever compared with never consuming human milk was associated with significantly lower odds of overweight/obesity at 12 to 21 years of age in females (OR 0.83 [95% CI 0.72, 0.95]); however, the association in males was closer to the null and nonsignificant (OR 0.90 [95% CI 0.76, 1.05]). In the subsample of siblings, ever compared with never consuming human milk was also associated with significantly lower odds of overweight/obesity at 12 to 21 years of age (OR 0.78 [95% CI 0.63, 0.97]). The within-family sibling analyses did not suggest any significant associations between ever, compared with never, consuming human milk and overweight/obesity at 12 to 21 years of age.
  - In the full sample, there were no significant associations between consuming human milk for durations of <3, 3-5.99, or 6-8.99 months, in comparison to never consuming human milk, and odds of overweight/obesity in males or in females at 12 to 21 years of age (OR [95% CI] 1.03 [0.85, 1.24], 0.81 [0.63, 1.04], and 0.86 [0.63, 1.17], respectively, in males, and 0.90 [0.74, 1.09], 0.82 [0.64, 1.05], and 0.73 [0.54, 1.00], respectively, in females). There was a significant association between consuming human milk for ≥9 months, compared with never, and odds of overweight/obesity at 12 to 21 years of age in females but not in males (OR [95% CI] 0.78 [0.64, 0.96] and 0.83 [0.67, 1.04], respectively). These analyses were not reported for the subsamples of siblings or discordant siblings.
  - In the subsample of siblings, there was a significant association between consuming human milk for ≥3 months, compared with never consuming human milk, and lower odds of overweight/obesity at 12 to 21 years of age (OR 0.69 [95% CI 0.54, 0.87]. This analysis was not reported for the full sample or the subsample of discordant siblings.
  - In a subsample of siblings with discordant exposures, there was no significant association between ever compared with never consuming human milk and difference in BMI z-score at 12 to 21 years of age when the lighter sibling was the one fed human milk (β= −0.004 ± 0.11) or when the heavier sibling was the one fed human milk (β=− 0.09 ± 0.11). This analysis was not reported for the full sample or the subsample of siblings.
4. Child Development Supplement of the Panel Study of Income Dynamics (CDS)
  Metzger and McDade^27^ examined a sample of children from the CDS in the United States. The sample consisted of children born between 1984 and 1993 with complete data on both infant feeding and BMI. The authors examined ever versus never consuming human milk as a dichotomous variable, which was obtained by recall from the primary caregiver when participants were between 4 and 13 years of age. Height and weight data were collected by study staff, but the specific methods were not reported. The outcomes of interest were BMI z-score as a continuous variable, and BMI considered as 2 separate dichotomous variables (1) 50^th^ percentile as a cut-off and (2) overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves). The authors conducted analyses in the full sample at 9 to 19 years of age (N=2591) using both an ordinary least squares model and a fixed-effects model, in a sibling subsample (N=976, including 118 siblings with discordant exposures), and in a subsample of siblings with differences in both feeding and BMI status (N=30 to 44).
  - In the full sample, ever compared with never consuming human milk was significantly associated with a 0.150 ± 0.065 (p <0.05) unit lower BMI z-score. In the sibling subsample, ever compared with never consuming human milk was significantly associated with a 0.397 ± 0.176 (p<0.05) unit lower BMI z-score in the fixed-effects models, but with a non-significantly 0.152 ± 0.106 unit lower BMI z-score in the ordinary least squares model.
  - In the sub-sample of participants with differences in both feeding and BMI status, ever compared with never consuming human milk was not significantly associated with the odds of having a BMI >50^th^ percentile (OR ~1.00 and ~1.30 from fixed effects and ordinary least squares regression models, respectively).
  - In the sub-sample of participants with differences in both feeding and BMI status, ever compared with never consuming human milk was significantly associated with a lower odds of overweight/obesity (OR ~0.60, p <0.01, and ~ 0.40, p<0.05, respectively from fixed effects and ordinary least squares regression models).

Table 1 Evidence examining the relationship between ever, compared with never, consuming human milk and body composition, including obesity, from studies that conducted within-family comparisons of siblings^a^

Article; Study design (Study name); Country | Ever vs never consuming human milk exposure^b^ | Outcome^c^ | Significant findings | Nonsignificant findings
Hawkins 2019 ^14^; RC (Linked CENTURY Study); U.S. | Initiated BF vs Did not initiate BF (ref) | BMIz* (β [95% CI])
Hawkins 2019 ^14^; RC (Linked CENTURY Study); U.S. | Initiated BF vs Did not initiate BF (ref) | @ 2 y
Hawkins 2019 ^14^; RC (Linked CENTURY Study); U.S. | Initiated BF vs Did not initiate BF (ref) | In the full sample (N=55,058) | −0.06 [−0.09, −0.04]
| | In subsample of siblings (N=21,455) | −0.06 [−0.10, −0.02]
| | In the subsample of siblings with discordant outcomes (N=2260) | | −0.04 [−0.10, 0.03]
| | @ 5 y
| | In the full sample (N=43,893) | −0.09 [−0.11, −0.07]
| | In the subsample of siblings (N=17,083) | −0.09 [−0.13, −0.06]
| | In the subsample of siblings with discordant outcomes (N=3249) | −0.07 [−0.13, −0.01]
| | OB* (OR [95% CI])
| | @ 2 y
| | In the full sample (N=55,058) | 0.80 [0.73, 0.87]
| | In the subsample of siblings (N=21,445) | 0.80 [0.69, 0.92]
| | In the subsample of siblings with discordant outcomes (N=2260) | | 0.97 [0.72, 1.32]
| | @ 5 y
| | In the full sample (N=43,893) | 0.77 [0.72, 0.83]
| | In the subsample of siblings (N=17,081) | 0.77 [0.69, 0.87]
| | In the subsample of siblings with discordant outcomes (N=3249) | | 0.94 [0.74, 1.20]
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* vs Not OB* (ref) (β ± SE) @ 3-11 y
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In the full sample
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Probit model (N=16,650 observations) | −0.018 ± 0.008^d^
| | Instrumental variable model (N=15,050 observations) | | −0.016 ± 0.010
| | In the subsample of siblings
| | at the same point in time (mean 5.9 y and 9.2 y for younger and older siblings, respectively) (N=7919 observations) | | 0.012 ± 0.017; NS
| | at the same age (mean 6.6 y) (N=4471 observations) | | −0.021 ± 0.023; NS
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | BMI (β ± SE, kg/m2) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In the full sample (N=8,237) | −0.449 ± 0.094; p<0.001
| | In the subsample of siblings (N=7,319) | −0.413 ± 0.101; p<0.001
| | In the subsample of siblings with discordant exposures (N=1,773) | | −0.141 ± 0.188; NS
| | OB* (β ± SE) @ 4-14 y
| | In the full sample (N=8,237) | −0.342 ± 0.066; p<0.001
| | In the subsample of siblings (N=7,319) | −0.369 ± 0.074; p<0.001
| | In subsample of siblings with discordant exposures (N=1,773) | | −0.173 ± 0.164; NS
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | BMI (β ± SE, kg/m2) @ 10-18 y
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | In the full sample (N=7417, 9486) | | −0.41 ± 0.07; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | −0.34 ± 0.16; p<0.10
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 0.40 ± 0.33;NS
| | OWOB* (OR ± SE from logit) @ 10-18 y
| | In the full sample (N=7417, 9486) | | 0.79 ± 0.03; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | 0.87 ± 0.08; NS
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 1.32 ± 0.21; p<0.10
| | OB* (OR ± SE from logit) @ 10-18 y
| | In the full sample (N=7417, 9486) | | 0.77 ± 0.04; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | 0.88 ± 0.11; NS
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 1.17 ± 0.25; NS
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | In the full sample
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | In males (N= 2787, 3142) | | 0.90 [0.76, 1.05]
| | In females (N= 2975, 3094) | 0.83 [0.72, 0.95]
| | In the subsample of siblings (N=860, 840) | 0.78 [0.63, 0.97]
| | In the subsample of siblings with discordant exposures and outcomes (N=224)
| | Odds that the non-OW sibling was ever BF and the OW sibling was never BF vs both siblings OW and never BF (ref) | | 0.52 [0.22, 1.24]
| | Odds that the non-OW sibling was ever BF and the OW sibling was never BF vs both siblings non-OW and never BF (ref) | | 1.22 [0.64, 2.32]
| | Odds that the OW sibling was ever BF and the non-OW sibling was never BF vs both siblings OW and never BF (ref) | | 2.03 [0.64, 6.43]
| | Odds that the OW sibling was ever BF and the non-OW sibling was never BF vs both siblings non-OW and never BF (ref) | | 1.27 [0.65, 2.50]
| | BMIz* difference (β ± SE) @ 12-21 y
| | In the subsample of siblings with discordant exposures
| | Lighter sibling BF (N=224=112 pairs) | | − 0.004 ± 0.11
| | Heavier sibling BF (N=224=112 pairs) | | − 0.09 ± 0.11
| BF ≥3 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y in the subsample of siblings | 0.69 [0.54, 0.87]
| BF <3 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF <3 mo vs Never BF (ref) | In the full sample
| BF <3 mo vs Never BF (ref) | In males (N=889, 3142) | | 1.03 [0.85, 1.24]
| | In females (N= 910, 3094) | | 0.90 [0.74, 1.09]
| BF 3-5.99 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF 3-5.99 mo vs Never BF (ref) | In the full sample
| BF 3-5.99 mo vs Never BF (ref) | In males (N=593, 3142) | | 0.81 [0.63, 1.04]
| | In females (N= 728, 3094) | | 0.82 [0.64, 1.05]
| BF 6-8.99 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF 6-8.99 mo vs Never BF (ref) | In the full sample
| BF 6-8.99 mo vs Never BF (ref) | In males (N=474, 3142) | | 0.86 [0.63, 1.17]
| | In females (N= 425, 3094) | | 0.73 [0.54, 1.00]
| BF ≥9 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF ≥9 mo vs Never BF (ref) | In the full sample
| BF ≥9 mo vs Never BF (ref) | In males (N=830, 3142) | | 0.83 [0.67, 1.04]
| | In females (N=607, 3094) | 0.78 [0.64, 0.96]
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | BMIz* (mean ± SE) @ 9-19 y
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | In full sample (N=2591) | −0.150 ± 0.065; p<0.05
| | In sibling subsample (N=976, including 118 siblings with discordant exposures)
| | Ordinary least squares model | | −0.152 ± 0.106
| | Fixed-effects model | −0.397 ± 0.176; p<0.05
| | BMI >50^th^ %ile* vs <50^th^ %ile* (ref) (OR) @ 9-19 y in sibling subsample (N=30 to 44 with differences in both feeding and BMI status)
| | Ordinary least squares model | | ~1.00; NS
| | Fixed-effects model | | ~1.30; NS
| | OWOB* vs Not OWOB (ref) (OR) @ 9-19 y in sibling subsample (N=30 to 44 with differences in both feeding and BMI status)
| | Ordinary least squares model | ~0.60; p<0.01
| | Fixed-effects model | ~0.40; p<0.05
| | OB* vs Not OB* (ref) (OR) @ 9-19 y in sibling subsample (N=30 to 44 with differences in both feeding and BMI status)
| | Ordinary least squares model | | ~0.70; NS
| | Fixed-effects model | ~0.20; p<0.01

a Abbreviations: %ile – percentile, Add Health – National Longitudinal Study of Adolescent Health, BF – breastfeeding/breastfed, BMI – body mass index, BMIz – BMI z-score, CDS – Child Development Supplement of the Panel Study of Income Dynamics, CI – confidence interval, mo – months, CS – cross sectional, NLSY79 – National Longitudinal Survey on Youth 1979 Cohort, NS – nonsignificant, OB – obesity, OR – odds ratio, OWOB – overweight and obesity, PC – prospective cohort study, RC – retrospective cohort study, ref – reference, SE – standard error, U.S. – United States of America, y – years

b Exposures, from the articles included in the body of evidence, which address ever vs never consuming human milk, or vice versa

c Notations used for growth references: *CDC, †WHO, ‡IOTF, §Country-specific

d Anderson et al (2003) did not explicitly state that this finding was significant; however the text of the article implied that it was significant

#### Description of the evidence examining the relationship between ever, compared with never, consuming human milk and overweight and/or obesity at 2 years of age and older (Table 2)

Thirty articles, published between 2003 and 2019, were identified that met the inclusion criteria and examined ever, compared with never, consuming human milk and overweight and/or obesity.^1–11,14–17,19–22,26,27,30–32,35–37,39–41^ They presented evidence from 21 independent studies. Four of the 21 studies were also described in the section about evidence from siblings (i.e., Linked CENTURY Study, Children of NLSY79, Add Health, and CDS). A description of the studies is presented below by age group (i.e., 2 to 5 years, 6 to 11 years, 12 to 19 years, and 20 years and older).

##### Studies with evidence in multiple age groups

1 Generation Rotterdam (Generation R) Study
  Durmus et al (2011),^9^ Heppe et al,^16^ and Durmus et al (2014)^8^ examined samples of children who participated in the Generation R Study conducted in the Netherlands. All samples consisted of singleton infants who had available information on infant feeding. Heppe et al^16^ additionally restricted the sample to include only Caucasian infants. Durmus et al (2011)^9^ examined 2 dichotomous variables: never consuming human milk compared with (1) consuming human milk for >6 months, and (2) consuming human milk exclusively until 4 months. Heppe et al^16^ and Durmus et al (2014)^8^ examined never consuming human milk compared with ever consuming human milk (irrespective of duration) as a dichotomous variable. Infant-feeding data were obtained from clinical delivery reports at birth, and by maternal report at 2, 6 and 12 months of age. The outcome of interest in all 3 studies was overweight and obesity (combined). Durmus et al (2011)^9^ defined overweight/obesity based on the Dutch growth reference charts (BMI >1 SDS, corresponding to an approximate adult BMI of >25 kg/m^2^) at 2 and 3 years of age (N=5074 at both ages). Heppe et al^16^ and Durmus et al (2014)^8^ defined overweight/obesity based on the cut-offs provided by the International Obesity Taskforce (IOTF) at approximately 4 years (N=3610), and 6 years of age (N=5063), respectively. Anthropometric data were measured by trained research staff using standardized protocols. Standing height, rather than recumbent lengths, were measured after 14 months of age.
  - Durmus et al (2011)^9^ found no significant associations between never consuming human, compared with consuming human milk for >6 months and the odds of overweight/obesity at 2 or at 3 years of age (OR [95% CI] ~1.5 [~0.9, ~2] and ~0.9 [~0.8, ~2], respectively). Likewise, the authors found no significant associations between never consuming human milk, compared with consuming human milk exclusively until 4 months of age, and the odds of overweight/obesity at 2 or at 3 years of age (OR [95% CI] ~1.5 [~0.8, ~2] and ~1.5 [~0.8, 2], respectively).
  - Heppe et al^16^ and Durmus et al (2014)^8^ found no significant associations between never consuming human milk compared with ever consuming human milk and the odds of overweight/obesity at 4 and at 6 years of age (OR [95% CI] 0.77 [0.47, 1.28] and ~0.8 [~0.6, ~1.3], respectively).
2 Lurbe et al^22^ examined a sample of children enrolled in a prospective cohort study conducted in Spain. The sample included singleton term infants (≥37 weeks gestational age) born via vaginal delivery at the Hospital General at the University of Valencia. The sample was 100% white Spanish and approximately 70% of the sample were considered appropriate weight for gestational age. The authors compared infants who were fed human milk at birth with infants who were not fed human milk at birth, as reported by the mother at birth. The outcome of interest was obesity (i.e., BMI z-score >2 SD based on the 2007 WHO growth standard) at 5 and 10 years of age (N=145 and 100 and 5 and 10 years of age, respectively). Weight and height data were measured by study staff.
  - Lurbe et al^22^ found that ever consuming human milk was associated with a significantly lower relative risk of obesity compared with never consuming human milk (β −0.190, p=0.022) at 5 years of age. The association was, however, no longer significant at 10 years of age (β −0.032, p=0.760).
3 Moschonis et al^30^ presented analyses conducted on 4 European cohorts: Avon Longitudinal Study of Parents and Children (ALSPAC), Etude des Déterminants pré et post natals de la santé et du développement de l’Enfant (EDEN), EuroPrevall, and Generation XXI, conducted in the United Kingdom, France, Greece, and Portugal, respectively. Infant-feeding data were collected by parent report via questionnaire at 6 and 15 months of age in ALSPAC, at 4, 8, and 12 months of age in EDEN, at 15 months of age in Generation XXI, and at 12, 24, and 30 months of age in EuroPrevall. The authors examined never consuming human milk, compared with consuming human milk for ≥6 months, as a dichotomous variable. Height and weight were measured at each study site and used to identify participants who were overweight and obese (combined, using IOTF cutoffs) at 4 (N=6522), 9 (N=7540), and 13 years of age (N=6124) in the ALSPAC cohort, at 4 years of age in the EuroPrevall (N=309) and Generation XXI (N=3387) cohorts, and at 5 years of age (N=1070) in EDEN cohort.
  - Moschonis et al^30^ found no significant associations between never consuming human milk, compared with consuming milk for ≥6 months, and the odds of overweight/obesity at 4, 9, or 13 years of age (OR ~0.8, ~1.2, and ~1.1, respectively; CIs not reported) in ALSPAC, at 4 years of age in EuroPrevall and Generation XXI (OR ~1.5 and ~1.2, respectively; CIs not reported), and at 5 years of age in the EDEN cohort (OR ~1.0; CI not reported).
4 Millennium Cohort Study (MCS)
  Weng et al^41^ and Massion et al^26^ examined samples of children who participated in the MCS, a nationally representative sample of children born in the United Kingdom between September 2000 and January 2002. Children living in disadvantaged areas and ethnic minorities were oversampled to adequately represent hard-to-reach populations. Weng et al^41^ restricted their sample to infants who were singletons born at term. Weng et al^41^ examined ever (irrespective of duration) compared with never consuming human milk as a dichotomous variable, while Massion et al^26^ examined consuming human milk for >4 months versus never consuming human milk as a dichotomous variable. Infant-feeding data were obtained by parent report at the first interview when infants were between 6 and 12 months of age (mean age of 9.2 months). The outcome of interest was overweight and obesity (combined; defined using IOTF cutoffs) at 3 years of age (N=10,810 in the study by Weng et al^41^) and 11 years of age (N=11,764 in the study by Massion et al^26^). Children’s heights and weights were measured by trained research staff using standardized protocols.
  - Weng et al^41^ found a significant association between never consuming human milk, compared with ever consuming human milk, and higher odds of overweight/obesity at 3 years of age (OR 1.25 [95% CI 1.09, 1.42]).
  - Massion et al^26^ found a significant association between never consuming human milk, compared with consuming human milk for >4 months, and a higher relative risk of overweight/obesity at 11 years of age (RR ~1.1 [95% CI ~1, ~1.25], p<0.05).
5 Children of the National Longitudinal Survey on Youth 1979 Cohort (Children of NLSY79)
  Anderson et al (2003),^3^ Colen and Ramey,^6^ and Huang et al^17^ examined samples of children and adolescents whose mothers were part of the National Longitudinal Survey on Youth 1979 Cohort from the United States. Anderson et al (2003)^3^ examined offspring who were 3 to 11 years of age between 1986 and 1996, Colen and Ramey^6^ examined offspring who were 4 to 14 years of age between 1986 and 2010 and born after the year 1978, and Huang et al^17^ examined children who had outcome data at 10 years of age and who had completed at least 8 waves of biannual data collection between 1986 and 2008. Colen and Ramey^6^ reported that about 75% of participants were non-Hispanic white, and Huang et al^17^ reported that about 42% were white, 35% were African American and 22% were Latino.
  All of the articles examined ever versus never consuming human milk as a dichotomous variable. Infant-feeding data were obtained by maternal report at biannual survey rounds starting in 1986.
  All of the articles used height and weight data. In the articles by Anderson et al (2003)^3^ and Colen and Ramey,^6^ height and weight were measured for most participants (i.e., in the article by Anderson et al (2003), 15% of children’s height and 22% of children’s weight were reported by mothers; in the article by Colen and Ramey, approximately 36% of child and adolescent height and weight data were reported by mothers or participants). In the article by Huang et al,^17^ height and weight were self-reported. All of the articles examined obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) as a dichotomous variable.
  Anderson et al (2003)^3^ conducted analyses on the full sample (N=16,650 observations using a probit model and N=15,050 observations using an instrumental variable model), and on subsamples of siblings measured at the same point in time (mean 5.9 and 9.2 years of age for the younger and older siblings, respectively; N=7919 observations), and at the same age (mean age of 6.6 years; N=4471 observations).
  - In the full sample, children who were ever fed human milk had an approximately 1.8% decrease in the likelihood of being obese relative to children never fed human milk at 3 to 11 years of age (β = −0.018 ± 0.008 and −0.016 ± 0.010, from probit and instrumental variable models, respectively; p-values were not reported, but the instrumental variable model was described as non-signficant).
  - In both sibling subsamples (i.e., with outcomes measured at the same age and at the same time point), being fed human milk was not significantly associated with the likelihood of being obese at 3 to 11 years of age (β = −0.021 ± 0.023 and 0.012 ± 0.017, respectively).
  Colen and Ramey^6^ conducted analyses on the full sample (N=8237 participants), on a subsample of siblings (N=7319 participants), and on a second subsample of siblings with discordant infant feeding (i.e., siblings fed differently during infancy; N=1773 participants).
  - In the full sample and sibling subsample, ever compared with never consuming human milk was associated with a significantly lower log odds of obesity at 4 to 14 years of age (β = −0.342 ± 0.066 and −0.369 ± 0.074, respectively; p<0.001 for both). In the discordant sibling subsample, the association was in the same direction but was smaller and lacked statistical significance (β = −0.173 ± 0.164).
  Huang et al^17^ conducted analyses on the full sample (N=5156).
  - Huang et al^17^ found that ever, compared with never, consuming human milk was associated with significantly lower odds of obesity at 10 years (OR: 0.79, p<0.05; CI not reported).
6 Prevention and Incidence of Asthma and Mite Allergy (PIAMA) cohort
  Ruijsbroek et al^37^ and Pluyman et al^36^ examined samples of children that participated in the PIAMA study from the Netherlands, which was a birth cohort study and prospective follow-up of (1) participants in an intervention study of mite-impermeable mattress and pillow covers, and (2) participants in a natural-history study in which no intervention was applied. The sample for the intervention arm of the study consisted of children of allergic mothers (mothers with at least 1 of the following: asthma ever, pet allergy, house dust mite allergy or nasal allergy such as hay fever). The sample for the natural-history study consisted of children born to both allergic and non-allergic mothers. Ruijsbroek et al^37^ examined never consuming human milk, compared with consuming human milk for >16 weeks, as a dichotomous variable. Pluyman et al^36^ examined consuming human milk (irrespective of duration) and consuming human milk for 3 different durations (<3 months, 3 to <6 months and ≥6 months) compared to never consuming human milk. Infant-feeding data were collected prospectively by parental report at 3 months of infant age. In the article by Ruijsbroek et al,^37^ the outcomes of interest were overweight and obesity (combined) and obesity, defined using IOTF cut-offs, at 3 to 8 years of age (N=3963). From 3 to 8 years of age, anthropometric data were collected via parental recall (based on doctor or nurse report if measured within the last 3 months, or measured by parents), but specific methods were not reported. In the article by Pluyman et al,^36^ the outcome of interest was overweight and obesity (combined), defined using the IOTF cutoff, at 12 years of age (N=2787). At 12 years of age, height and weight were measured by study staff.
  - Ruijsbroek et al^37^ found no significant associations between never consuming human milk, compared with consuming human milk for >16 weeks, and the odds of overweight/obesity or obesity at 3 to 8 years of age (OR [95% CI] 1.08 [0.91, 1.29] and 1.44 [0.95, 2.18], respectively); however the wide confidence interval around the odds ratio for obesity may indicate an insufficient sample size to detect the outcome.
  - In contrast, Pluyman et al,^36^ found that ever consuming human milk (irrespective of duration), compared with never consuming human milk, was significantly associated with lower odds of overweight/obesity at 12 years of age (OR 0.61 [95% CI 0.38, 0.97]). When the authors divided the group ever fed human milk into 3 categories of duration (i.e., <3 months, 3 -<6 months, ≥6 months), the odds ratios were similar, but the confidence intervals were wider so the associations lacked statistical significance (OR [95% CI] 0.63 [0.37, 1.08], 0.55 [0.30, 1.00], and 0.61 [0.36, 1.06], respectively).
7 National Longitudinal Study of Adolescent Health (Add Health)
  Evenhouse and Reilly,^10^ Bohr et al,^5^ and Nelson et al^32^ presented evidence from the Add Health study from the United States. This cohort is a nationally representative sample of 10- to 18-year-olds in grades 7 to 12 during the 1994-1995 school year (baseline). Low-income, African-American, and Hispanic youth were oversampled. Nelson et al^32^ excluded members of the cohort if they had severe disabilities or pregnancies, were Native Americans, or had graduated from high school, and reported that the sample was 72% non-Hispanic white, 13% non-Hispanic black, 11% Hispanic and 3% Asian.
  All 3 articles examined ever versus never consuming human milk as a dichotomous variable.
  In addition, Nelson et al^32^ examined dichotomous comparisons of participants who were never fed human milk with participants who were fed human milk for different durations (i.e., ≥3 months, <3 months, 3-5.99 months, 6-8.99 months and ≥9 months). Infant-feeding data were obtained by parent recall at 10 to 18 years (i.e., baseline).
  The articles looked at outcomes at baseline (i.e., 10 to 18 years), 2 years later (i.e., 12 to 21 years), and 14 years later (i.e., 24 to 33 years). Evenhouse and Reilly^10^ examined overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) and obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) as dichotomous variables at 10 to 18 years of age. Nelson et al^32^ examined overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) as a dichotomous variable at 12 to 21 years of age. Bohr et al^5^ examined obesity (i.e., BMI ≥30 kg/m^2^) as a dichotomous variable when members of the cohort were 24 to 33 years of age. None of the articles reported the methods for anthropometric data collection.
  Evenhouse and Reilly^10^ conducted analyses on the full sample (N=16,903), on a subsample of siblings (N=3773) and on a second subsample of siblings with discordant infant feeding (i.e., sibships in which 1 sibling was ever fed human milk and the other was never fed human milk; N=576).
  - In the full sample, the sibling subsample, and the discordant sibling subsample, ever compared with never consuming human milk was not significantly associated with odds of overweight/obesity (OR = 0.79 ± 0.03, 0.87 ± 0.08, 1.32 ± 0.21, respectively; p<0.10 for the full-sample and discordant-sibling subsample analyses), or obesity (OR = 0.77 ± 0.04, 0.88 ± 0.11, 1.17 ± 0.25, respectively; p<0.10 for the full-sample analysis) at 10 to 18 years of age.
  Nelson et al^32^ conducted analyses on the full sample stratified by sex (N=5929 males, 6069 females), on a subsample of siblings (N=1700), and on subsamples of siblings with discordant infant feeding and outcomes (i.e., in which the overweight sibling had been fed human milk and the non-overweight sibling had not, and in which the overweight sibling had not been fed human milk and the non-overweight sibling had; N=224 discordant siblings).
  - In the full sample, ever compared with never consuming human milk was associated with significantly lower odds of overweight/obesity at 12 to 21 years of age in females (OR 0.83 [95% CI 0.72, 0.95]); however, the association in males was closer to the null and nonsignificant (OR 0.90 [95% CI 0.76, 1.05]). In the subsample of siblings, ever compared with never consuming human milk was also associated with significantly lower odds of overweight/obesity at 12 to 21 years of age (OR 0.78 [95% CI 0.63, 0.97]). The within-family sibling analyses did not suggest any significant associations between ever, compared with never, consuming human milk and overweight/obesity at 12 to 21 years of age.
  - In the full sample, there were no significant associations between consuming human milk for durations of <3, 3-5.99, or 6-8.99, in comparison to never consuming human milk, and odds of overweight/obesity in males or in females at 12 to 21 years of age (OR [95% CI] 1.03 [0.85, 1.24], 0.81 [0.63, 1.04], and 0.86 [0.63, 1.17], respectively, in males, and 0.90 [0.74, 1.09], 0.82 [0.64, 1.05], and 0.73 [0.54, 1.00], respectively in females). There was a significant association between consuming human milk for ≥9 months, compared with never, and odds of overweight/obesity at 12 to 21 years of age in females but not in males (OR [95% CI] 0.78 [0.64, 0.96] and 0.83 [0.67, 1.04], respectively). These analyses were not reported for the subsamples of siblings or discordant siblings.
  - In the subsample of siblings, there was a significant association between consuming human milk for ≥3 months, compared with never consuming human milk, and lower odds of overweight/obesity at 12 to 21 years of age (OR 0.69 [95% CI 0.54, 0.87]. This analysis was not reported for the full sample or the subsample of discordant siblings.
  Bohr et al^5^ conducted analyses in an unrelated sample (N=4648) and a sibling pair sample (N=1179).
  - In the unrelated sample, the odds of being obese at 24 to 33 years were significantly lower in those ever compared with never fed human milk (OR [95% CI] 0.854 [0.75, 0.97], p=0.018). In the sibling pair sample, the direction and magnitude of effect was the same, but the association was not significant (0.854 [0.64, 1.13], p=0.277).
8 Child Development Supplement of the Panel Study of Income Dynamics (CDS)
  Metzger and McDade^27^ examined a sample of children from the U.S.-based CDS. The sample consisted of children born between 1984 and 1993 with complete data on both infant feeding and BMI. The authors examined ever versus never consuming human milk as a dichotomous variable, which was obtained by recall from the primary caregiver when participants were between 4 and 13 years of age. Height and weight data were collected by study staff, but the specific methods were not reported. The outcome of interest was BMI considered as 2 separate dichotomous variables (1) 50^th^ percentile as a cut-off and (2) overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves). The authors conducted analyses in the full sample at 9 to 19 years of age (N=2591) using both an ordinary least squares model and a fixed-effects model, in a sibling subsample (N=976, including 118 siblings with discordant exposures), and in a subsample off siblings with differences in both feeding and BMI status (N=30 to 44).
  - In the sub-sample of participants with differences in both feeding and BMI status, ever compared with never consuming human milk was not significantly associated with the odds of having a BMI >50^th^ percentile (OR ~ 1.00 and ~1.30 from fixed effects and ordinary least squares regression models, respectively).
  - In the sub-sample of participants with differences in both feeding and BMI status, ever compared with never consuming human milk was significantly associated with a lower odds of overweight/obesity (OR ~0.60 (p <0.01) and ~ 0.40 (p<0.05), respectively from fixed effects and ordinary least squares regression models, respectively).

##### Studies with evidence from 2 to 5 years of age

9 Growing Up in Scotland (GUS)
  Abraham et al^1^ examined data from the U.K.-based prospective cohort study GUS, which had a representative sample of Scottish infants from 130 geographically clustered areas across Scotland. Infants were born between June 2004 and May 2005 and were selected at random from child benefit records. The authors examined ever consuming human milk (irrespective of duration) compared to never consuming human milk. Infant-feeding data were reported by the primary caregiver (typically mothers) when the child was between 9 and 12 months of age. The outcome of interest was overweight/obesity (combined) at 45-48 months of age (i.e., BMI z-score ≥1.04 based on the 1990 U.K. growth reference curves; N=3515). Height and weight were measured by study staff, but specific methods were not reported.
  - Abraham et al^1^ found a nonsignificant association between ever, compared with never, consuming human milk and lower odds of overweight/obesity at 45-48 months (OR 0.81 [95% CI 0.64,1.01]).

Anderson et al (2003)^3^: See number 5, above

10 Anderson et al (2014)^2^ examined data from a cohort of infants born between 2005 and 2009 who participated in the Supplemental Nutrition Program for Women, Infants and Children (WIC) in Hawaii, United States. The majority of the participants were of Native Hawaiian (62%) and Asian (25%) ancestry. The authors examined dichotomous comparisons of infants who consumed human milk for <1 month (N=3769), 1-2 months (N=4864), 3-5 months (N=3119), or ≥6 months (N=2192) with infants who never consumed human milk (N=1197). Infant-feeding data were collected from mothers by WIC staff. The outcome of interest was overweight and obesity (combined; i.e., BMI ≥85^th^ percentile based on CDC growth curves) at 2 years of age. Height and weight were measured by WIC staff, but the methods used were not reported.
  - There was a significant association between consuming human milk for ≥6 months, compared with never consuming human milk, and a lower prevalence ratio of overweight/obesity at 2 years of age (prevalence ratio 0.82 [95% CI 0.72, 0.94], p<0.05). The associations between consuming shorter durations of human milk (i.e., <1, 1-2, and 3-5 months), compared with never consuming human milk, and the odds of overweight and obesity at 2 years of age were closer to the null and nonsignificant (OR [95% CI] 0.97 [0.86, 1.09], 0.96 [0.85, 1.08], and 0.99 [0.89, 1.12], respectively).

Colen and Ramey^6^: See number 5, above

Durmus et al (2011)^9^: See number 1, above

11 Feldman-Winter et al^11^ examined a cohort of infants born in an urban Baby-Friendly hospital in the United States that primarily served racial and ethnic minority groups and families with a low SES. Participants were singletons, born adequate weight for gestational age, about 70% Hispanic, 20% black, and 5% white, and about 85% were WIC participants. The authors compared infants who consumed infant formula exclusively for the first week of life (N=12) with infants who consumed human milk exclusively for the first week of life (N=71). Infant-feeding data were collected from post-delivery medical records and from maternal report during a home visit when infants were 7 days old. The outcome of interest was overweight and obesity (combined; i.e., BMI ≥85th percentile based on WHO growth curves) at 2 years of age.
  - The authors found no significant association between consuming infant formula exclusively for the first week of life, compared with consuming human milk exclusively for the first week of life, and odds of overweight/obesity at 2 years of life (OR 0.7 [95% CI 0.1, 7.0], p=0.79). The study was underpowered, because at this Baby-Friendly hospital, there were few infants who were exclusively fed infant formula.
12 Linked CENTURY Study
  Hawkins et al^14^ examined a sample of singleton children from the U.S.-based Linked CENTURY Study. Participants were from an existing clinical database of well-child visits at Atrius Health in Eastern Massachusetts. The authors examined initiation of human milk feeding as a dichotomous variable, which was obtained from hospital records at birth. Height and weight were measured by medical assistants at 2 and 5 years of age. The outcome of interest was obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) as a dichotomous variable. The authors conducted analyses in the full sample (N=55,058 at 2 years and 43,893 at 5 years), in a subsample consisting of siblings (N=21,455 at 2 years and 17,083 at 5 years) and in a subsample of siblings with discordant outcomes (N= 2260 at 2 years and 3249 at 5 years).
  - In the full sample, initiating, compared with not initiating, human milk feeding was associated with significantly lower odds of obesity at both 2 and 5 years of age (OR [95% CI] = 0.80 [0.73, 0.87] and 0.77 [0.72, 0.83], respectively). In the subsample of families with more than 1 sibling, the odds were the same with slightly wider confidence intervals (OR [95% CI] = 0.80 [0.69, 0.92] and 0.77 [0.69, 0.87], respectively). In the subsample of siblings with discordant outcomes, initiating human milk feeding was not significantly associated with obesity at 2 or 5 years of age, and the odds ratios were closer to the null (OR [95% CI] = 0.97 [0.72, 1.32] and 0.94 [0.74, 1.20], respectively).

Heppe et al^16^: See number 1, above

13 Layte et al^19^ presented evidence from a nationally representative sample of infants in Ireland who were 9 months old in 2008-2009. Participants were predominantly of Irish nationality (86%). The authors compared infants who consumed human milk for <3 months (N=386), <6 months (N=543), and ≥6 months (N=870) with infants who never consumed human milk (N=4743). Authors did not indicate whether the <6 month variable included or excluded infants fed human milk <3 months. Infant-feeding data were collected by maternal reports via interview at 9 months. Study staff measured participant height and weight at 3 years of age, which were used to identify participants who were obese using the IOTF threshold.
  - Layte et al^19^ found a significant association between consuming human milk for ≥6 months, compared with never consuming human milk, and lower odds of obesity at 3 years of age (OR 0.51, p<0.001; CI not reported). The associations between consuming human milk for shorter durations (i.e., <3 and <6 months), compared with never consuming human milk, were closer to the null and nonsignificant (OR 0.96, p=0.79 and 0.97, p=0.87, respectively; CIs not reported).
14 Lee et al^20^ retrospectively examined a cohort of 38,049 infants born in Korea in 2008 who had completed 7 routine medical check-ups at 4 to 6, 9 to 12, 18 to 24, 30 to 36, 42 to 48, 54 to 60, and 66 to 72 months of age. The authors compared infants who were mixed-fed from birth to 4-6 months and infants who consumed human milk exclusively from birth to 4-6 months with infants who consumed infant formula exclusively from birth to 4-6 months. Infant-feeding data were reported by parents during the 4-6 month medical check-up and extracted from the National Health Insurance Service database. The outcome of interest was overweight/obesity (combined; i.e., BMI >90^th^ percentile based on the Korean National Growth Charts) at 30-36, 42-48, 54-60, and 66-72 months of age. Height and weight were measured during the medical check-ups. The authors stratified the analyses by birthweight category (i.e., normal birth weight, high birthweight).
  - In the high-birthweight subsample, there were significant associations between being mixed-fed from birth to 4 to 6 months, compared with being exclusively formula fed from birth to 4 to 6 months, and lower odds of overweight/obesity at 30-36 months and 42-48 months (OR [95% CI] 0.66 [0.48, 0.92] and 0.69 [0.50, 0.97], respectively). The association at 54-60 months was in the same direction but was slightly attenuated and lacked statistical significance (OR 0.75 [95% CI 0.54, 1.03]). The association at 66 to 72 months was close to the null (OR 1.02 [95% CI 0.72, 1.45]).
  - In the normal-birthweight subsample, there were no significant associations between being mixed-fed from birth to 4 to 6 months, compared with being exclusively formula fed from birth to 4 to 6 months, and the odds of overweight/obesity at 30-36, 42-48, 54-60, or 66-72 months of age (OR [95% CI] 0.94 [0.86, 1.02]), 0.97 [0.89, 1.05]), 0.92 [0.84, 1.00], and 0.95 [0.88, 1.04], respectively).
  - In the high-birthweight subsample, there were significant associations between being fed human milk exclusively from birth to 4-6 months, compared with being fed infant formula exclusively from birth to 4-6 months, and lower odds of overweight/obesity at 30-36 and 54-60 months of age (OR [95% CI] 0.73 [0.56, 0.96] and 0.69 [0.53, 0.90], respectively). The association at 42-48 months was in the same direction but the confidence interval included the null (OR 0.76 [95% CI 0.58, 1.00]. The association at 66-72 months was in the opposite direction, but was nonsignificant (OR 1.24 [95% CI 0.92, 1.66].
  - In the normal-birthweight subsample, there were significant associations between being fed human milk exclusively from birth to 4-6 months, compared with being fed infant formula exclusively from birth to 4-6 months, and lower odds of overweight/obesity at 30-36, 42-48, 54-60, and 66-72 months of age (OR [95% CI] 0.75 [0.70, 0.81], 0.85 [0.79, 0.91], 0.87 [0.81, 0.93], and 0.87 [0.81, 0.93], respectively).
15 Early Childhood Longitudinal Study-Birth (ECLS-B)
  Li et al^21^ and Moss and Yeaton^31^ examined samples from the ECLS-B cohort from the United States. Participants were a nationally representative sample born in the United States in 2001 to mothers who were at least 15 or 16 years of age, respectively.^21,31^ Moss and Yeaton^31^ restricted the sample to participants with a birthweight ≥1500g. Li et al^21^ reported that 42% of participants were non-Hispanic white, 16% were non-Hispanic black, 20% were Hispanic, 11% were Asian, and 11% had other racial/ethnic backgrounds; Moss and Yeaton^31^ did not report similar information. Both articles examined ever consuming human milk, compared with never consuming human milk, as a dichotomous variable. Moss and Yeaton^31^ secondarily stratified infants by their timing of introduction to complementary foods. Infant-feeding data were collected by maternal interview at 9 months and 4 years. Li et al^21^ assessed obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) at 4 years (N=8150). Moss and Yeaton^31^ assessed obesity as well as overweight (i.e., BMI ≥85^th^ -94^th^ percentile based on CDC growth curves) and healthy weight (i.e., BMI <85^th^ percentile based on CDC growth curves, including underweight infants) at 2 years (total analytic N=7200) and 4 years (total analytic N=6950). Height and weight were measured by trained research staff.
  - Li et al^21^ found that ever consuming human milk, compared with never consuming human milk, was associated with significantly lower odds of obesity at 2 years of age (OR 0.76 [95% CI 0.63, 0.92]).
  - Likewise, Moss and Yeaton^31^ found that ever consuming human milk, compared with never consuming human milk, was associated with significantly lower odds of obesity (compared with overweight) at 2 and at 4 years of age (OR [95% CI] 0.64 [0.51, 0.80], p<0.001, and 0.67 [0.53, 0.85], p<0.01 respectively). The associations with normal weight (compared with overweight) at 2 and at 4 years were closer to the null and nonsignificant (OR [95% CI] 1.08 [0.89, 1.31] and 0.94 [0.75, 1.18] respectively).
  - In secondary analyses that incorporated the timing of participants’ introduction to complementary foods:
    ○ When all infants were introduced to complementary foods <4 months, there was a significant association between ever consuming human milk, compared with never consuming human milk, and lower odds of obesity (compared with healthy weight) at 2 years of age (OR 0.64 [95% CI 0.47, 0.86], p<0.01). However the association with obesity at 4 years of age was slightly attenuated and nonsignificant (OR 0.72 [95% CI 0.49, 1.06], p<0.10). The associations with overweight (compared with healthy weight) at 2 and at 4 years were nonsignificant (OR [95% CI] 0.89 [0.62, 1.29] and 0.91 [0.62, 1.34] respectively).
    ○ When infants ever fed human milk were introduced to complementary foods at 4-5 months and infants never fed human milk were introduced to complementary foods at <4 months, there were significant associations between ever consuming human milk, compared with never consuming human milk, and lower odds of obesity (compared with health weight) at 2 and at 4 years of age (OR [95% CI] 0.38 [0.29, 0.51], p<0.001 and 0.45 [0.33, 0.61], p<0.001, respectively). The associations with overweight (compared with healthy weight) at 2 and at 4 years were nonsignificant (OR [95% CI] 0.92 [0.67, 1.28] and 0.80 [0.55, 1.16], respectively).
    ○ Likewise, when infants ever fed human milk were introduced to complementary foods at ≥6 months and infants never fed human milk were introduced to complementary foods at <4 months, there were significant associations between ever consuming human milk, compared with never consuming human milk, and lower odds of obesity (compared with health weight) at 2 and at 4 years of age (OR [95% CI] 0.38 [0.27, 0.53], p<0.001 and 0.51 [0.36, 0.72], p<0.001, respectively). The associations with overweight (compared with healthy weight) at 2 and at 4 years were nonsignificant (OR [95% CI] 0.82 [0.58, 1.15] and 0.81 [0.54, 1.22] respectively).

Lurbe et al^22^: See number 2, above

Moschonis et al^30^: See number 3, above

Moss and Yeaton^31^: See number 15, above

16 First Baby Study (FBS)
  Pattison et al^35^ conducted a secondary analysis of a sample of children enrolled in the FBS in the United States. Children included in the analyses were first-born, primarily white (approximately 84% of sample) and had available data on human milk consumption. The authors compared ever consuming human milk (irrespective of duration), as well as consuming human milk for 2 different durations (0-6 months and <6 months) with never consuming human milk. Infant-feeding data were collected prospectively via maternal interviews at 1, 6, and 12 months of age. The outcomes of interest were overweight/obesity (combined; i.e., BMI ≥85^th^ percentile using CDC growth curves) and obesity (i.e., BMI ≥95^th^ percentile using CDC growth curves) at 36 months of age (N=1626, 867, and 870 for analyses comparing ever, 0-6 months, and >6 months with never consuming human milk, respectively). Height and weight were measured and reported by mothers.
  - Pattison et al^35^ found that ever consuming human milk was associated with a significantly lower odds of overweight/obesity at 36 months compared with never consuming human milk (OR [95% CI] 0.63 [0.41, 0.96]). Likewise, the authors found that consuming human milk for >6 months was associated with a significantly lower odds of overweight/obesity at 36 months of age compared with never consuming human milk (OR 0.54 [95% CI 0.34, 0.85]). The association between consuming human milk for 0-6 months and the odds of overweight/obesity was in the same direction and of similar magnitude, but was not statistically significant (OR 0.68 [95% CI 0.44, 1.05]).
  - Ever consuming human milk (irrespective of duration), consuming human milk for 0-6 months, and consuming human milk for >6 months were all significantly associated with a lower odds of obesity at 36 months compared to never consuming human milk (OR [95% CI] 0.51 [0.30, 0.86], 0.54 [0.32, 0.94] and 0.43 [0.24, 0.78], respectively).

Ruijsbroek et al^37^: See number 6, above

17 Thorland et al^39^ examined first-born children from low-income families enrolled in the Nurse-Family Partnership in the United States between 2007 and 2010. The authors examined dichotomous comparisons of infants who consumed human milk for 1-3, 4-8, 8-12, or >20 weeks with infants who never consumed human milk. Infant-feeding data were collected by parent report. The outcome of interest was high weight-for-length (WFL) status (i.e., WFL ≥97.7^th^ percentile based on the WHO growth curves) at 24 months of age (N=6,383). Length and weight were measured by Nurse-Family Partnership staff during home visits using NHANES guidelines.
  - There was a significant association between consuming human milk for >20 weeks, compared with never consuming human milk, and lower odds of high WFL status at 24 months of age (OR 0.60 [95% CI 0.41, 0.88], p <0.05). The associations between shorter durations of human milk consumption (i.e., 1-3, 4-8, and 8-20 weeks), compared with never consuming human milk, and high WFL status at 24 months of age were in the same direction but were attenuated and nonsignificant (OR [95% CI] 0.82 [0.60, 1.12]), 0.95 [0.71–1.28]), and 0.91 [0.66–1.27], respectively).
18 Project Viva
  van Rossem et al^40^ presented evidence from Project Viva, conducted in the United States. Participants were born ≥34 weeks gestational age, and had mothers who attended a prenatal visit at 1 of 8 affiliated medical offices in eastern Massachusetts between 1999-2002. Participants were predominantly Caucasian (74%) from highly educated families. The authors examined dichotomous comparisons of infants who (a) consumed human milk for <6 months, (b) consumed human milk for 6 months, and (c) consumed human milk exclusively for 6 months with infants who never consumed human milk. Infant-feeding data were collected from maternal interview at 6 months. The outcome of interest was obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) at 3 years of age (N=713). Height and weight were measured by trained research staff using standardized protocols. The authors used analyses without and with adjustment for change in weight-for-age z-score from birth to 6 months, in order to determine the mediating effects of infant weight gain.
  - In the analyses that did not control for infant weight gain, there was a significant association between consuming human milk exclusively for 6 months, compared with never consuming human milk, and lower odds of obesity at 3 years of age (OR 0.21 [95% CI 0.07, 0.68]). Consuming human milk non-exclusively for <6 or 6 months, compared with never consuming human milk were not significantly associated with the odds of obesity at 3 years; the odds were closer to the null (OR [95% CI] 0.90 [0.40, 2.03] and 0.88 [0.37, 2.10], respectively).
  - In the analyses that did control for infant weight gain, there were no significant associations between consuming any human milk for <6 or 6 months or consuming human milk exclusively for 6 months and the odds of obesity at 3 years of age (OR [95% CI] 0.85 [0.33, 2.18], 1.44 [0.53, 3.96], and 0.29 [0.08, 1.05], respectively).

Weng et al^41^: See number 4, above

##### Studies with evidence from 6 to 11 years of age

Anderson et al (2003)^3^: See number 5, above

19 Bjertnaes et al^4^ examined a sample of children enrolled in a prospective cohort study conducted in Norway. Children included in the cohort started school in Oppland County, a predominantly rural county, in 2007. The authors examined consuming human milk (irrespective of duration), compared to never consuming human milk, as a dichotomous variable. Infant-feeding data were recalled by parents at routine school entry health assessments when children were 5-6 years of age. The outcome of interest was overweight/obesity (combined) at approximately 8 years of age (N=951) using BMI cut-offs provided by the IOTF. Height and weight were measured by school nurses, but specific methods were not reported.
  - Bjertnaes et al^4^ found no significant association between ever, compared with never, consuming human milk and the odds of overweight/obesity at 8 years of age (OR 0.99 [95% CI 0.48, 2.02], p=0.97)

Colen and Ramey^6^: See number 5, above

20 Groningen Long-Chain Polyunsaturated Fatty Acid (LCPUFA) Study
  de Jong et al^7^ conducted a randomized controlled trial, the Groningen LCPUFA Study, in the Netherlands of infants born between 37 and 42 weeks of gestational age. Infants whose mothers chose to formula feed were randomly assigned to receive either a control formula from birth to 6 months of age, or an AA- and DHA-supplemented formula from birth to 3 months of age followed by a control formula from 3 to 6 months of age. A human milk-fed reference group was also enrolled in the study, and infants in the reference group were given AA- and DHA-supplemented formula until 3 mo of age, and control formula from 3 to 6 mo of age if human milk feeding stopped <2 months. The authors compared the reference group fed human milk with each of the randomized formula-fed groups. Mothers reported infant-feeding data prospectively in daily diaries until 8 months of infant age. The outcome of interest was overweight/obesity (combined; defined using IOTF BMI cut-offs) at 9 years of age (N=218-250). Height and weight were measured by study staff using standardized protocols.
  - de Jong et al^7^ found no significant associations between a nonrandomized group ever fed human milk and randomized groups fed either a standard infant formula or an AA- and DHA-supplemented infant formula, and the risk of overweight/obesity at 9 years (data NR).

Durmus et al (2014)^8^: See number 1, above

Evenhouse and Reilly^10^: See number 7, above

21 Growing Right onto Wellness (GROW)
  Heerman et al^15^ examined a prospective cohort from the GROW study conducted in the United States. Participants were from low-income families (e.g., 100% qualified for services for underserved populations such as Medicaid or WIC, 43% were food insecure), mostly Hispanic (i.e., 63% Hispanic Mexican, 28% Hispanic non-Mexican, 9% non-Hispanic), and considered to be at high risk for developing obesity at baseline when they were 3 to 5 years of age (i.e., BMI ≥50^th^ and <95^th^ percentile based on CDC growth curves). Infant-feeding data were collected by parent recall at baseline, and the authors examined a dichotomous comparison of human milk consumption for ≥6 months compared to never consuming human milk. Trained study staff measured height and weight. The outcome of interest was obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) when participants were a mean of about 7 years of age (N=356).
  - In this high-risk cohort, consuming human milk for ≥6 months, compared with never consuming human milk, was not significantly associated with the odds of obesity at approximately 7 years of age (OR 0.88 [95% CI 0.48, 1.60]).

Huang et al^15^: See number 5, above

Lurbe et al^22^: See number 2, above

Massion et al^26^: See number 4, above

Metzger and McDade^27^: See number 8, above

Moschonis et al^30^: See number 3, above

Ruijsbroek et al^37^: See number 6, above

##### Studies with evidence from 12 to 19 years of age

Colen and Ramey^6^: See number 5, above

Evenhouse and Reilly^10^: See number 7, above

Metzger and McDade^27^: See number 8, above

Moschonis et al^30^: See number 3, above

Nelson et al^32^: See number 7, above

Pluyman et al^36^: See number 6, above

##### Studies with evidence at 20 years of age or later

Bohr et al^5^: See number 7, above

Nelson et al^32^: See number 7, above

#### Synthesis and assessment^ii^ of the evidence examining the relationship between ever, compared with never, consuming human milk and overweight and/or obesity at 2 years of age and older (Table 2)

Thirty articles presented evidence from 21 independent studies about the relationship between ever, compared with never, consuming human milk and overweight and/or obesity at 2 years of age and older.^1–11,14–17,19–22,26,27,30–32,35–37,39–41^ A synthesis and assessment of the evidence follows.

[underlined: Consistency:] The evidence had strong consistency.

Fourteen of the 21 studies (18 of 30 articles) found significant associations between ever, compared with never, consuming human milk and overweight and/or obesity.^2,5,6,14,17,19–22,26,27,31,32,35,36,39–41^ The significant associations were consistent in direction. They were all in the direction of ever consuming human milk being associated with lower risk of overweight and/or obesity across a wide range ages from childhood into adulthood:

- 2 years of age^2,14,31,39^
- 3 years of age^19,20,35,40,41^
- 4 years of age^20,21,31^
- 5 years of age^14,20,22^
- 6 years of age^20^
- 10 years of age^17^
- 11 years of age^26^
- 12 years of age^36^
- 4 to 14 years of age^6^
- 9 to 19 years of age^27^
- 12 to 21 years of age^32^
- 24 to 33 years of age^5^

The remaining 7 studies found no significant associations between ever, compared with never, consuming human milk and overweight and/or obesity. One of the 7 studies^1^ reported a marginal association between ever, compared with never, consuming human milk and lower odds of overweight/obesity at 45-48 months (OR 0.81 [95% CI 0.64, 1.01]). The remaining 6 studies may have had insufficient statistical power for some of their analyses, which may account for the lack of statistical significance (see Precision, below).^4,7,9,11,15,30^

A closer examination of the evidence from 7 studies (which divided participants into more than 1 group of infants ever fed human milk, based on how long infants consumed human milk, and compared these infants with infants never fed human milk) revealed a trend in the data. Five of the 7 articles found that a longer duration of human milk consumption (e.g., >6 months), compared to never consuming human milk, was significantly associated with lower risk of overweight and/or obesity, but that a shorter duration (e.g., <6 months) was not:

- Anderson et al (2014)^2^ found a significant association between consuming human milk for ≥6 months, compared with never consuming human milk, and a lower prevalence ratio of overweight/obesity at 2 years of age. However, associations between shorter durations of human milk consumption (i.e., <1, 1-2, and 3-5 months) and overweight/obesity at 2 years of age were not statisitically significant.
- Layte et al^19^ found a significant association between consuming human milk for ≥6 months, compared with never consuming human milk, and lower odds of obesity at 3 years of age. However, associations between shorter durations of human milk consumption (i.e., <3 and <6 months) and obesity at 3 years of age were not statistically significant.
- Pattison et al^35^ found significant associations between consuming human milk for >6 months, compared with never consuming human milk, and lower odds of overweight/obesity at 36 months of age and obesity at 36 months of age, and between consuming human milk for 0-6 months, compared with never consuming human milk, and lower odds of obesity at 36 months. However, the association between the shorter duration of 0-6 months of human milk consumption and overweight/obesity at 36 months was nonsignificant.
- Thorland et al^39^ found a significant association between consuming human milk for >20 weeks, compared with never consuming human milk, and lower odds of high weight-for-length status (defined as ≥97.7^th^ percentile based on WHO growth curves) at 24 months of age. However, associations between shorter durations of human milk consumption (i.e., 1-3, 4-8, and 8-20 weeks) and high weight-for-length status at 24 months of age were not statistically significant.
- Nelson et al^32^ found a significant association between consuming human milk for ≥9 months, compared with never consuming human milk, and lower odds of overweight/obesity at 12-21 years of age in females (but not males). However, associations between shorter durations of human milk consumption (i.e., <3, 3-5.99, and 6-8.99 months) and overweight/obesity at 12-21 years of age were not statistically significant in either sex.

The remaining 2 articles did not find a similar trend. Pluyman et al^36^ reported marginal associations for all durations of human milk consumption that were compared to never consuming human milk (OR [95% CI]: 0.63 [0.37, 1.08], 0.55 [0.30, 1.00], and 0.61 [0.36, 1.06] for durations of <3, 3-6, and ≥6 months, respectively). In the article by van Rossem et al^40^, the associations between consuming human milk for <6 and ≥6 months, compared with never consuming human milk, had wide confidence intervals (i.e., 0.40 to 2.03 and 0.37 to 2.10, respectively), suggesting insufficient statistical power.

The evidence from 4 studies was of particular interest because the studies conducted within-family analyses of siblings to reduce confounding from genetic and environmental factors (factors that siblings share) (see Risk of Bias, below). The evidence had some inconsistencies.

- Metzger and McDade^27^ reported significant associations from within-family sibling analyses between ever, compared with never, consuming human and lower odds of overweight/obesity at 9 to 19 years of age.
- The other 3 studies did not find significant associations from within-family sibling analyses between ever, compared with never, consuming human milk and overweight and/or obesity.^3,6,10,14,32^ Rather, they tended to find that the significant associations found in the full-sample analyses were no longer significant. This may be due, in part, to the much smaller sample size available for the within-family analyses; however, in 2 articles it was clear that there was an attenuation of the estimated association that had been seen in the full-sample analyses.^6,14^ These findings suggest that some of the association between ever consuming human milk and lower risk of overweight and/or obesity is explained by confounding. Unfortunately, none of these studies had within-family analyses that compared infants who consumed human milk for different durations with infants who never consumed human milk. Therefore, it is not possible to comment on whether the trend described above (i.e., that longer durations of human milk consumption may be important) is true for sibling analyses.
- We also examined BMI (or BMI z-score) as a continuous variable in 3 studies that had both full-sample and within-family analyses.^6,10,14^ The findings were inconsistent. One study did not find significant associations between ever, compared with never, consuming human milk and BMI at 10 to 18 years of age in either analysis.^10^ One study found a significant association between ever, compared with never, consuming human milk and lower BMI at 4 to 14 years of age in the full-sample analysis that was attenuated and nonsignificant in the within-family analysis.^6^ One study found significant associations between initiating, compared with not initiating, human milk feeding and lower BMI z-score at 2 and at 5 years of age in the full sample, and a slight attenuation of the estimated associations in the within-family analyses so that the association at 5 years of age was still statistically significant.^14^

[underlined: Precision:] The evidence had strong precision.

The body of evidence had 21 studies, and 14 of them had sufficient statistical power to detect significant associations. Of the remaining 7 studies, 1 reported a marginal association in the same direction as, and with a similar magnitude to, the associations with statistical significance,^1^ and 6 may have had insufficient statistical power for some of their analyses, which may account for the lack of statistical significance. For example, Feldman-Winter et al^11^ compared infants fed infant formula exclusively with infants fed human milk exclusively for their first week of life following birth in a Baby-Friendly hospital, where the proportion of infants never fed human milk was low. As a result, the confidence interval around the odds ratio was very wide (i.e., 0.1 to 7.0). Associations reported by 3 other studies had confidence intervals greater than 1, which suggests insufficient statistical power.^4,9,15^ The final 2 studies did not report confidence intervals^7,30^; however, de Jong et al^7^ had fewer participants than many of the samples in the body of evidence (about 250 participants), and Moschonis et al^30^ suggested that analyses of their sample from the EuroPrevall cohort (about 300 participants) in their multi-cohort study, in particular, may have been underpowered.

[underlined: Directness:] The evidence had strong directness.

Most of the articles reported study objectives that included the examination of human milk consumption and overweight and/or obesity.

[underlined: Generalizability:] The evidence had moderate generalizability.

Eleven of the 21 studies (16 of 30 articles) were conducted in the United States.^2,3,5,6,10,11,14,15,17,21,27,31,32,35,39,40^ The studies included nationally representative samples, samples with racial and ethnic diversity, and samples from families with low income.

One study was conducted in Korea,^20^ and the remaining 9 studies (13 of 30 articles) were conducted in European countries.^1,4,7–9,16,19,22,26,30,36,37,41^ There may be some concerns about the generalizability of the evidence from these studies to U.S. populations, which may have higher risk of overweight and obesity than the populations from which participants were sampled in the non-U.S. studies.

The generalizability of the evidence may also be limited because few studies examined the outcomes past childhood. Only 5 studies examined outcomes in adolescents,^6,10,27,30,32,36^ and only 1 examined outcomes in adults.^5,32^

[underlined: Risk of bias:] There is a moderate likelihood that the design and conduct of the studies have prevented or minimized bias.

Infant-feeding decisions can be strongly socially patterned; therefore, in this entirely observational body of evidence, the risk of bias from confounding is of particular concern. Four studies conducted within-family analyses of siblings to reduce confounding from shared genetic and environmental factors.^3,6,10,14,27,32^ However, these studies were prone to other risks of bias. For example, the Add Health and CDS studies asked mothers to recall how they fed their offspring during infancy when those offspring were between 4 and 18 years of age.^10,27,32^ In addition, in the Children of NLSY79 study some participants reported their own height and weight,^3,6^ and in the Add Health study the methods used to collect outcome data were not reported.^10,32^

None of the remaining 17 studies controlled for all of the key confounders identified on the analytic framework. In particular, studies tended not to account for complementary feeding practices and childhood diet. In addition, the studies had other risks of bias, which varied between studies (Tables 3 and 4).

[underlined: Publication bias:]

In addition to the graded elements of the assessment of the evidence, above, it is important to give consideration to publication bias, which may be present given the consistency of the evidence.

[underlined: Conclusion:] Given this synthesis and assessment of the evidence, we conclude that moderate evidence from observational studies indicates that ever, compared with never, consuming human milk is associated with lower risk of overweight and obesity at 2 years of age and older, particularly if the duration of human milk consumption is 6 months or longer.

Table 2 Evidence examining the relationship between ever, compared with never, consuming human milk and overweight and/or obesity at 2 years of age and older^a^

Article; Study design (Study name); Country | Ever vs never consuming human milk exposure^b^ | Outcome^c^ | Significant findings | Nonsignificant findings
Outcomes from 2 to 5 years
Abraham 2012 ^1^; PC (GUS); U.K. | Ever BF vs Never BF (ref) | OWOB§ (OR [95% CI] @ 45-48 mo (N=1913 BF/not OWOB; 231 BF/OWOB; 1176 Not BF/not OWOB; 195 Not BF/OWOB) | | 0.81 [0.64,1.01]
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* vs Not OB* (ref) (β ± SE) @ 3-11 y
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In the full sample
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Probit model (N=16,650 observations) | −0.018 ± 0.008^d^
| | Instrumental variable model (N=15,050 observations) | | −0.016 ± 0.010
| | In the subsample of siblings
| | at the same point in time (mean 5.9 y and 9.2 y for younger and older siblings, respectively) (N=7919 observations) | | 0.012 ± 0.017; NS
| | at the same age (mean 6.6 y) (N=4471 observations) | | −0.021 ± 0.023; NS
Anderson 2014 ^2^; RC; U.S. | BF <1 mo vs Never BF (ref) | OWOB (prevalence ratio [95% CI]) @ 2 y (N=3769, 1197) | | 0.97 [0.86, 1.09]
| BF 1-2 mo vs Never BF (ref) | OWOB (prevalence ratio [95% CI]) @ 2 y (N=4864, 1197) | | 0.96 [0.85, 1.08]
| BF 3-5 mo vs Never BF (ref) | OWOB (prevalence ratio [95% CI]) @ 2 y (N=3119, 1197) | | 0.99 [0.89, 1.12]
| BF ≥6 mo vs Never BF (ref) | OWOB (prevalence ratio [95% CI]) @ 2 y (N=2192, 1197) | 0.82 [0.72, 0.94]; p<0.05
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* (β ± SE) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 3 age groups
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In Full Sample (N=8,237) | −0.342 ± 0.066; p<0.001
| | In sibling sample (N=7,319) | −0.369 ± 0.074; p<0.001
| | In discordant sibling sample (N=1,773) | | −0.173 ± 0.164; NS
Durmus 2011 ^9^; PC (Generation R); Netherlands | Never BF vs BF >6 mo (ref) | OWOB§ (OR [95% CI]) @ 2 y (Total analytic N=5074) | | ~1.5 [~0.9, ~2]
| | OWOB§ (OR [95% CI]) @ 3 y (Total analytic N=5074) | | ~0.9 [~0.8, ~2]
| Never BF vs EBF until 4 mo (ref) | OWOB§ (OR [95% CI]) @ 2 y (Total analytic N=5074) | | ~1.5 [~0.8, 2]
| | OWOB§ (OR [95% CI]) @ 3 y (Total analytic N=5074) | | ~1.5 [~0.8, 2]
Feldman-Winter 2018 ^11^; PC; U.S. | Exclusive FF 1st week vs EBF 1st wk (ref) | OWOB† (OR [95% CI]) @ 2 y (N=58 EBF/not OWOB; 13 EBF/OWOB; 11 Exclusive FF/not OWOB; 1 Exclusive FF/OWOB) | | 0.7 [0.1, 7.0]; p=0.79
Hawkins 2019 ^14^; RC (Linked CENTURY Study); U.S. | Initiated BF vs Did not initiate BF (ref) | OB* (OR [95% CI])
Hawkins 2019 ^14^; RC (Linked CENTURY Study); U.S. | Initiated BF vs Did not initiate BF (ref) | @ 2 y
Hawkins 2019 ^14^; RC (Linked CENTURY Study); U.S. | Initiated BF vs Did not initiate BF (ref) | In full sample (Total analytic N=55,058) | 0.80 [0.73, 0.87]
| | In subsample of families with more than 1 sibling (Total analytic N=21,445) | 0.80 [0.69, 0.92]
| | In subsample of siblings with discordant outcomes (Total analytic N=2260) | | 0.97 [0.72, 1.32]
| | @ 5 y
| | In full sample (Total analytic N=43,893) | 0.77 [0.72, 0.83]
| | In subsample of families with more than 1 sibling (Total analytic N=17,081) | 0.77 [0.69, 0.87]
| | In subsample of siblings with discordant outcomes (Total analytic N=3249) | | 0.94 [0.74, 1.20]
Heppe 2013 ^16^; PC (Generation R); Netherlands | No BF vs BF (ref) | OWOB‡ (OR [95% CI]) @ ~4 y (Total analytic N=335 OWOB; 3275 Not OWOB) | | 0.77 [0.47, 1.28]
Layte 2014 ^19^; PC; Ireland | BF <3 mo vs Never BF (ref) | OB ‡ (OR) @ 3 y (N=386, 4743) | | 0.96; p=0.79
| BF <6 mo vs Never BF (ref) | OB ‡ (OR) @ 3 y (N=543, 4743) | | 0.97; p=0.87
| BF ≥6 mo vs Never BF (ref) | OB ‡ (OR) @ 3 y (N=870, 4743) | 0.51; p<0.001
Lee 2019 ^20^; RC; Korea | Mixed-fed from birth to 4-6 mo vs FF from birth to 4-6 mo (ref) | OWOB§ (OR [95% CI])
Lee 2019 ^20^; RC; Korea | Mixed-fed from birth to 4-6 mo vs FF from birth to 4-6 mo (ref) | @ 30-36 mo
Lee 2019 ^20^; RC; Korea | Mixed-fed from birth to 4-6 mo vs FF from birth to 4-6 mo (ref) | In normal birthweight subsample (N=6,816 NBW MF, 10,780 NBW FF) | . | 0.94 [0.86, 1.02]
| | In high birthweight subsample (N=303 HBW MF, 416 HBW FF) | 0.66 [0.48, 0.92] | .
| | @ 42-48 mo
| | In normal birthweight subsample (N=6,816 NBW MF, 10,780 NBW FF) | . | 0.97 [0.89, 1.05]
| | In high birthweight subsample (N=303 HBW MF, 416 HBW FF) | 0.69 [0.50, 0.97] | .
| | @ 54-60 mo
| | In normal birthweight subsample (N=6,816 NBW MF, 10,780 NBW FF) | . | 0.92 [0.84, 1.00]
| | In high birthweight subsample (N=303 HBW MF, 416 HBW FF) | . | 0.75 [0.54, 1.03]
| | @ 66-72 mo
| | In normal birthweight subsample (N=6,816 NBW MF, 10,780 NBW FF) | . | 0.95 [0.88, 1.04]
| | In high birthweight subsample (N=303 HBW MF, 416 HBW FF) | | 1.02 [0.72, 1.45]
| EBF from birth to 4-6 mo vs FF from birth to 4-6 mo (ref) | OWOB§ (OR [95% CI])
| EBF from birth to 4-6 mo vs FF from birth to 4-6 mo (ref) | @ 30-36 mo
| EBF from birth to 4-6 mo vs FF from birth to 4-6 mo (ref) | In normal birthweight subsample (N=16,487 NBW EBF, 10,780 NBW FF) | 0.75 [0.70, 0.81] | .
| | In high birthweight subsample (N=673 HBW EBF, 416 HBW FF) | 0.73 [0.56, 0.96] | .
| | @ 42-48 mo
| | In normal birthweight subsample (N=16,487 NBW EBF, 10,780 NBW FF) | 0.85 [0.79, 0.91] | .
| | In high birthweight subsample (N=673 HBW EBF, 416 HBW FF) | . | 0.76 [0.58, 1.00]
| | @ 54-60 mo
| | In normal birthweight subsample (N=16,487 NBW EBF, 10,780 NBW FF) | 0.87 [0.81, 0.93] | .
| | In high birthweight subsample (N=673 HBW EBF, 416 HBW FF) | 0.69 [0.53, 0.90] | .
| | @ 66-72 mo
| | In normal birthweight subsample (N=16,487 NBW EBF, 10,780 NBW FF) | 0.87 [0.81, 0.93] | .
| | In high birthweight subsample (N=673 HBW EBF, 416 HBW FF) | . | 1.24 [0.92, 1.66]
Li 2011 ^21^; PC (ECLS-B); U.S. | Ever BF vs Never BF (ref) | OB* (OR [95% CI]) @ 4 y (N=5600, 2550) | 0.76 [0.63, 0.92]
Lurbe 2018 ^22^; PC; Spain | BF at birth vs Not BF at birth (ref) | OB (β, RR) @ 5 y (N=145) | −0.190; p=0.022
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | Never BF vs BF ≥6 mo (ref) | OWOB†‡ (OR)
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | Never BF vs BF ≥6 mo (ref) | @ 4 y
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | Never BF vs BF ≥6 mo (ref) | in ALSPAC cohort (N=6522) | | ~0.8; NS
| | in EuroPrevall cohort (N=309) | | ~1.5; NS
| | in Generation XXI cohort (N=3387) | | ~1.2; NS
| | @ 5 y in EDEN cohort (N=1070) | | ~1.0; NS
Moss 2014 ^31^; PC (ECLS-B); U.S. | Ever BF vs Never BF (ref) | OB* (OR [95% CI]) vs OW (ref)
Moss 2014 ^31^; PC (ECLS-B); U.S. | Ever BF vs Never BF (ref) | @ 2 y (Total analytic N=7200) | 0.64 [0.51, 0.80]; p<0.001
| | @ 4 y (Total analytic N=6950) | 0.67 [0.53, 0.85]; p<0.01
| | Healthy weight status* (OR [95% CI]) vs OW (ref) | | 1.08 [0.89, 1.31]
| | @ 2 y (Total analytic N=7200) | | 1.08 [0.89, 1.31]
| | @ 4 y (Total analytic N=6950) | | 0.94 [0.75, 1.18]
| Ever BF, CF <4 mo vs Never BF, CF <4 mo (ref) | OW* (OR [95% CI]) vs healthy weight status (ref) | | 0.89 [0.62, 1.29]
| Ever BF, CF <4 mo vs Never BF, CF <4 mo (ref) | @ 2 y (Total analytic N=7200) | | 0.89 [0.62, 1.29]
| | @ 4 y (Total analytic N=6950) | | 0.91 [0.62, 1.34]
| | OB* (OR [95% CI]) vs healthy weight status (ref) | 0.64 [0.47, 0.86]; p<0.01
| | @ 2 y (Total analytic N=7200) | 0.64 [0.47, 0.86]; p<0.01
| | @ 4 y (Total analytic N=6950) | | 0.72 [0.49, 1.06]; p<0.10
| Ever BF, CF 4-5 mo vs Never BF, CF <4 mo (ref) | OW* (OR [95% CI]) vs healthy weight status (ref) | | 0.92 [0.67, 1.28]
| Ever BF, CF 4-5 mo vs Never BF, CF <4 mo (ref) | @ 2 y (Total analytic N=7200) | | 0.92 [0.67, 1.28]
| | @ 4 y (Total analytic N=6950) | | 0.80 [0.55, 1.16]
| | OB* (OR [95% CI]) vs healthy weight status (ref) | 0.38 [0.29, 0.51]; p<0.001
| | @ 2 y (Total analytic N=7200) | 0.38 [0.29, 0.51]; p<0.001
| | @ 4 y (Total analytic N=6950) | 0.45 [0.33, 0.61]; p<0.001
| Ever BF, CF ≥6 mo vs Never BF, CF <4 mo (ref) | OW* (OR [95% CI]) vs healthy weight status (ref) | | 0.82 [0.58, 1.15]
| Ever BF, CF ≥6 mo vs Never BF, CF <4 mo (ref) | @ 2 y (Total analytic N=7200) | | 0.82 [0.58, 1.15]
| | @ 4 y (Total analytic N=6950) | | 0.81 [0.54, 1.22]
| | OB* (OR [95% CI]) vs healthy weight status (ref) | 0.38 [0.27, 0.53]; p<0.001
| | @ 2 y (Total analytic N=7200) | 0.38 [0.27, 0.53]; p<0.001
| | @ 4 y (Total analytic N=6950) | 0.51 [0.36, 0.72]; p<0.001
Pattison 2019 ^35^; RC (FBS); U.S. | Ever BF vs Never BF (ref) | OWOB vs no OWOB (OR [95% CI]) @ 36 mo (N=356 ever BF/OWOB, 42 never BF/OWOB, 1159 ever BF/not OWOB, 69 never BF/not OWOB) | 0.63 [0.41, 0.96]
| | OB vs No OB (OR [95% CI]) @ 36 mo (N=138 ever BF/OB, 24 never BF/OB, 1377 ever BF/No OB, 87 never B/No OB) | 0.51 [0.30, 0.86]
| BF 0-6 mo vs Never BF (ref) | OWOB vs No OWOB (OR [95% CI]) @ 36 mo (N=203 BF 0-6 mo/OWOB, 42 never BF/OWOB, 69 553 BF 0-6 mo/No OWOB, never BF/no OWOB) | | 0.68 [0.44, 1.05]
| | OB vs No OB (OR [95% CI]) @ 36 mo (N=83 BF 0-6 mo/OB, 24 never BF/OB, 673 BF 0-6 mo/No OB, 87 never BF/No OB) | 0.54 [0.32, 0.94]
| BF >6 mo vs Never BF (ref) | OWOB vs No OWOB (OR [95% CI]) @ 36 mo (N=153 BF >6 mo/OWOB, 42 never BF/OWOB, 606 BF >6 mo/No OWOB, 69 never BF/No OWOB) | 0.54 [0.34, 0.85]
| | OB vs No OB (OR [95% CI]) @ 36 mo (N=55 BF >6 mo/OB, 24 never BF/OB, 704 BF >6 mo/No OB, 87 never BF/No OB) | 0.43 [0.24, 0.78]
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | Never BF vs BF >16 wk (ref) | OWOB‡ (OR [95% CI]) in childhood (3-8 y) (Total analytic N=3963) | | 1.08 [0.91, 1.29]
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | Never BF vs BF >16 wk (ref) | Note: this analysis is across 2 age groups | | 1.08 [0.91, 1.29]
| | OB‡ (OR [95% CI]) in childhood (3-8 y) (N=NR) | | 1.44 [0.95, 2.18]
| | Note: this analysis is across 2 age groups | | 1.44 [0.95, 2.18]
Thorland 2017 ^39^; PC; U.S. | BF 1-3 wk vs Never BF (ref) | High WFL status (≥97.7 %ile †) (OR [95% CI]) @ 24 mo (N=6,383) | | 0.82 [0.60, 1.12]
| BF 4-8 wk vs Never BF (ref) | High WFL status (≥97.7 %ile †) (OR [95% CI]) @ 24 mo (N=6,383) | | 0.95 [0.71, 1.28]
| BF 8-20 wk vs Never BF (ref) | High WFL status (≥97.7 %ile †) (OR [95% CI]) @ 24 mo (N=6,383) | | 0.91 [0.66, 1.27]
| BF >20 wk vs Never BF (ref) | High WFL status (≥97.7 %ile †) (OR [95% CI]) @ 24 mo (N=6,383) | 0.60 [0.41, 0.88]; p <0.05
van Rossem 2011 ^40^; PC (Project Viva); U.S. | BF <6 mo vs Never BF (ref) | OB* vs normal weight status* (OR [95% CI]) @ 3 y (N=713)
van Rossem 2011 ^40^; PC (Project Viva); U.S. | BF <6 mo vs Never BF (ref) | In final model | | 0.90 [0.40, 2.03]
| | In final model, adjusted for change in infant WAZ from birth to 6 mo | | 0.85 [0.33, 2.18]
| BF 6 mo vs Never BF (ref) | OB* vs normal weight status* (OR [95% CI]) @ 3 y (N=713)
| BF 6 mo vs Never BF (ref) | In final model | | 0.88 [0.37, 2.10]
| | In final model, adjusted for change in infant WAZ from birth to 6 mo | | 1.44 [0.53, 3.96]
| EBF 6 mo vs Never BF (ref) | OB* vs normal weight status* (OR [95% CI]) @ 3 y (N=713)
| EBF 6 mo vs Never BF (ref) | In final model | 0.21 [0.07, 0.68]
| | In final model, adjusted for change in infant WAZ from birth to 6 mo | | 0.29 [0.08, 1.05]
Weng 2013 ^41^; PC (MCS); U.K. | Never BF vs Ever BF (ref) | OWOB ‡ (OR [95% CI]) @ 3 y (N=10810) | 1.25 [1.09 1.42]
Outcomes from 6 to 11 years
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* vs Not OB* (ref) (β ± SE) @ 3-11 y
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In the full sample
Anderson 2003 ^3^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Probit model (N=16,650 observations) | −0.018 ± 0.008^4^
| | Instrumental variable model (N=15,050 observations) | | −0.016 ± 0.010
| | In the subsample of siblings
| | at the same point in time (mean 5.9 y and 9.2 y for younger and older siblings, respectively) (N=7919 observations) | | 0.012 ± 0.017; NS
| | at the same age (mean 6.6 y) (N=4471 observations) | | −0.021 ± 0.023; NS
Bjertnaes 2019 ^4^; PC; Norway | Ever BF vs Never BF (ref) | OWOB‡ (OR [95% CI]) @ ~ 8 y | . | 0.99 [0.48, 2.02]; p=0.97
Bjertnaes 2019 ^4^; PC; Norway | Ever BF vs Never BF (ref) | (Total analytic N~200 OWOB, ~751 Not OWOB) | . | 0.99 [0.48, 2.02]; p=0.97
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* (β ± SE) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 3 age groups | −0.342 ± 0.066; p<0.001
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In Full Sample (N=8,237) | −0.342 ± 0.066; p<0.001
| | In sibling sample (N=7,319) | −0.369 ± 0.074; p<0.001
| | In discordant sibling sample (N=1,773) | | −0.173 ± 0.164; NS
de Jong 2011 ^7^; NRCT (Groningen LCPUFA Study); Netherlands | Ever BF vs Control FF 0-6 mo | Normal‡ (vs OWOB‡) BMI @ 9 y (Total analytic N=250) | | NS; data NR
| Ever BF vs AA- and DHA-supplemented FF 0-6 mo | Normal‡ (vs OW‡) BMI @ 9 y (Total analytic N=218) | | NS; data NR
Durmus 2014 ^8^; PC (Generation R); Netherlands | Never BF vs Ever BF (ref) | OWOB ‡ (OR [95% CI]) @ 6 y (N=385, 4678) | | ~0.8 [~0.6, ~1.3]
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | OWOB* (OR ± SE from logit) @ 10-18 y
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | In the full sample (N=7417, 9486) | | 0.79 ± 0.03; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | 0.87 ± 0.08; NS
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 1.32 ± 0.21; p<0.10
| | OB* (OR ± SE from logit) @ 10-18 y
| | Note: this analysis is across 2 age groups
| | In the full sample (N=7417, 9486) | | 0.77 ± 0.04; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | 0.88 ± 0.11; NS
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 1.17 ± 0.25; NS
Heerman 2019 ^15^; PC (GROW); U.S. | No BF vs BF ≥6 mo (ref) | OB* (OR [95% CI]) @ ~7 y (N=62 No BF/No OB, 29 No BF/OB, 167 BF/No OB, 98 BF/OB) | . | 0.88 [0.48, 1.60]
Huang 2014 ^15^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* (OR) @ 10 y (Total analytic N= 5156) | 0.79; p<0.05 (95% CI NR)
Lurbe 2018 ^22^; PC; Spain | BF at birth vs Not BF at birth (ref) | OB (β, RR) @ 10 y (N=100) | | −0.032; p=0.760
Massion 2016 ^26^; PC (MCS); U.K. | Never BF vs Any BF >4 mo (ref) | OWOB ‡ (RR [95% CI]) @ 11 y (Total analytic N=3445 OWOB, 8319 Not OWOB) | ~1.1 [~1, ~1.25]; p<0.05
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | BMI >50^th^ %ile* vs <50^th^ %ile* (ref) (OR) @ 9-19 y in sibling subsample
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | (N=30 to 44 with differences in both feeding and BMI status) | | ~1.00; NS
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | Ordinary least squares model
| | Fixed-effects model | | ~1.30; NS
| | OWOB* vs Not OWOB (ref) (OR) @ 9-19 y in sibling subsample
| | (N=30 to 44 with differences in both feeding and BMI status) | ~0.60; p<0.01
| | Note: this analysis is across 2 age groups
| | Ordinary least squares model
| | Fixed-effects model | ~0.40; p<0.05
| | OB* vs Not OB* (ref) (OR) @ 9-19 y in sibling subsample
| | (N=30 to 44 with differences in both feeding and BMI status) | | ~0.70; NS
| | Note: this analysis is across 2 age groups
| | Ordinary least squares model
| | Fixed-effects model | ~0.20; p<0.01
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | Never BF vs BF ≥6 mo (ref) | OWOB†‡ (OR) @ 9 y in ALSPAC cohort (N=7540) | | ~1.2; NS
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | Never BF vs BF >16 wk (ref) | OWOB‡ (OR [95% CI]) in childhood (3-8 y) (Total analytic N=3963) | | 1.08 [0.91, 1.29]
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | Never BF vs BF >16 wk (ref) | Note: this analysis is across 2 age groups | | 1.08 [0.91, 1.29]
| | OB‡ (OR [95% CI]) in childhood (3-8 y) (N=NR) | | 1.44 [0.95, 2.18]
| | Note: this analysis is across 2 age groups | | 1.44 [0.95, 2.18]
Outcomes from 12 to 19 years
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | OB* (β ± SE) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 3 age groups | −0.342 ± 0.066; p<0.001
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | Ever BF vs Never BF (ref) | In Full Sample (N=8,237) | −0.342 ± 0.066; p<0.001
| | In sibling sample (N=7,319) | −0.369 ± 0.074; p<0.001
| | In discordant sibling sample (N=1,773) | | −0.173 ± 0.164; NS
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | OWOB* (OR ± SE from logit) @ 10-18 y
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Ever BF vs Never BF (ref) | In the full sample (N=7417, 9486) | | 0.79 ± 0.03; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | 0.87 ± 0.08; NS
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 1.32 ± 0.21; p<0.10
| | OB* (OR ± SE from logit) @ 10-18 y
| | Note: this analysis is across 2 age groups
| | In the full sample (N=7417, 9486) | | 0.77 ± 0.04; p<0.10
| | In the subsample of siblings (N=1607, 2166) | | 0.88 ± 0.11; NS
| | In the subsample of siblings with discordant exposures (N=288, 288) | | 1.17 ± 0.25; NS
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | BMI >50^th^ %ile* vs <50^th^ %ile* (ref) (OR) @ 9-19 y in sibling subsample
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | (N=30 to 44 with differences in both feeding and BMI status) | | ~1.00; NS
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups | | ~1.00; NS
Metzger 2009 ^27^; PC (CDS); U.S. | Ever BF vs Never BF (ref) | Ordinary least squares model | | ~1.00; NS
| | Fixed-effects model | | ~1.30; NS
| | OWOB* vs Not OWOB (ref) (OR) @ 9-19 y in sibling subsample
| | (N=30 to 44 with differences in both feeding and BMI status) | ~0.60; p<0.01
| | Note: this analysis is across 2 age groups | ~0.60; p<0.01
| | Ordinary least squares model | ~0.60; p<0.01
| | Fixed-effects model | ~0.40; p<0.05
| | OB* vs Not OB* (ref) (OR) @ 9-19 y in sibling subsample
| | (N=30 to 44 with differences in both feeding and BMI status) | | ~0.70; NS
| | Note: this analysis is across 2 age groups | | ~0.70; NS
| | Ordinary least squares model | | ~0.70; NS
| | Fixed-effects model | ~0.20; p<0.01
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | Never BF vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 13 y in ALSPAC cohort (N=6124) | | ~1.1; NS
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | In the full sample
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | In males (N= 2787, 3142) | | 0.90 [0.76, 1.05]
| | In females (N= 2975, 3094) | 0.83 [0.72, 0.95]
| | In the subsample of siblings (N=860, 840) | 0.78 [0.63, 0.97]
| | In the subsample of siblings with discordant exposures and outcomes (N=224)
| | Odds that the non-OW sibling was ever BF and the OW sibling was never BF vs both siblings OW and never BF (ref) | | 0.52 [95% CI 0.22, 1.24]
| | Odds that the non-OW sibling was ever BF and the OW sibling was never BF vs both siblings non-OW and never BF (ref) | | 1.22 [95% CI 0.64, 2.32]
| | Odds that the OW sibling was ever BF and the non-OW sibling was never BF vs both siblings OW and never BF (ref) | | 2.03 [95% CI 0.64, 6.43]
| | Odds that the OW sibling was ever BF and the non-OW sibling was never BF vs both siblings non-OW and never BF (ref) | | 1.27 [95% CI 0.65, 2.50]
| BF ≥3 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y in the subsample of siblings | 0.69 [0.54, 0.87]
| BF ≥3 mo vs Never BF (ref) | Note: this analysis is across 2 age groups | 0.69 [0.54, 0.87]
| BF <3 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF <3 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF <3 mo vs Never BF (ref) | In the full sample
| BF <3 mo vs Never BF (ref) | In males (N=889, 3142) | | 1.03 [0.85, 1.24]
| | In females (N= 910, 3094) | | 0.90 [0.74, 1.09]
| BF 3-5.99 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF 3-5.99 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF 3-5.99 mo vs Never BF (ref) | In the full sample
| BF 3-5.99 mo vs Never BF (ref) | In males (N=593, 3142) | | 0.81 [0.63, 1.04]
| | In females (N= 728, 3094) | | 0.82 [0.64, 1.05]
| BF 6-8.99 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF 6-8.99 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF 6-8.99 mo vs Never BF (ref) | In the full sample
| BF 6-8.99 mo vs Never BF (ref) | In males (N=474, 3142) | | 0.86 [0.63, 1.17]
| | In females (N= 425, 3094) | | 0.73 [0.54, 1.00]
| BF ≥9 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF ≥9 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF ≥9 mo vs Never BF (ref) | In the full sample
| BF ≥9 mo vs Never BF (ref) | In males (N=830, 3142) | | 0.83 [0.67, 1.04]
| | In females (N=607, 3094) | 0.78 [0.64, 0.96]
Pluyman 2019 ^36^; PC (PIAMA); Netherlands | Ever BF vs Never BF (ref) | OWOB‡ (OR [95% CI]) @ 12 y (N=1288, 211) | 0.61 [0.38, 0.97]
| BF <3 mo vs Never BF (ref) | OWOB‡ (OR [95% CI]) @ 12 y (N=511, 211) | | 0.63 [0.37, 1.08]
| BF 3 to <6 mo vs Never BF (ref) | OWOB‡ (OR [95% CI]) @ 12 y (N=338, 211) | | 0.55 [0.30, 1.00]
| BF ≥6 mo vs Never BF (ref) | OWOB‡ (OR [95% CI]) @ 12 y (N=439, 211) | | 0.61 [0.36, 1.06]
Outcomes at 20 years or later
Bohr 2015 ^5^; PC (Add Health); U.S. | Ever vs Never BF (ref) | OB (OR [95% CI]) @ 24-33 y
Bohr 2015 ^5^; PC (Add Health); U.S. | Ever vs Never BF (ref) | In unrelated sample (N=4648) | 0.854 [0.75, 0.97]; p=0.018
| | In sibling pair sample (N=1179) | | 0.854 [0.64, 1.13]; p=0.277
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | Note: this analysis is across 2 age groups
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | In the full sample
Nelson 2005 ^32^; PC (Add Health); U.S. | Ever BF vs Never BF (ref) | In males (N= 2787, 3142) | | 0.90 [0.76, 1.05]
| | In females (N= 2975, 3094) | 0.83 [0.72, 0.95]
| | In the subsample of siblings (N=860, 840) | 0.78 [0.63, 0.97]
| | In the subsample of siblings with discordant exposures and outcomes (N=224)
| | Odds that the non-OW sibling was ever BF and the OW sibling was never BF vs both siblings OW and never BF (ref) | | 0.52 [95% CI 0.22, 1.24]
| | Odds that the non-OW sibling was ever BF and the OW sibling was never BF vs both siblings non-OW and never BF (ref) | | 1.22 [95% CI 0.64, 2.32]
| | Odds that the OW sibling was ever BF and the non-OW sibling was never BF vs both siblings OW and never BF (ref) | | 2.03 [95% CI 0.64, 6.43]
| | Odds that the OW sibling was ever BF and the non-OW sibling was never BF vs both siblings non-OW and never BF (ref) | | 1.27 [95% CI 0.65, 2.50]
| BF ≥3 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y in the subsample of siblings | 0.69 [0.54, 0.87]
| BF ≥3 mo vs Never BF (ref) | Note: this analysis is across 2 age groups | 0.69 [0.54, 0.87]
| BF <3 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF <3 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF <3 mo vs Never BF (ref) | In the full sample
| BF <3 mo vs Never BF (ref) | In males (N=889, 3142) | | 1.03 [0.85, 1.24]
| | In females (N= 910, 3094) | | 0.90 [0.74, 1.09]
| BF 3-5.99 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF 3-5.99 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF 3-5.99 mo vs Never BF (ref) | In the full sample
| BF 3-5.99 mo vs Never BF (ref) | In males (N=593, 3142) | | 0.81 [0.63, 1.04]
| | In females (N= 728, 3094) | | 0.82 [0.64, 1.05]
| BF 6-8.99 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF 6-8.99 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF 6-8.99 mo vs Never BF (ref) | In the full sample
| BF 6-8.99 mo vs Never BF (ref) | In males (N=474, 3142) | | 0.86 [0.63, 1.17]
| | In females (N= 425, 3094) | | 0.73 [0.54, 1.00]
| BF ≥9 mo vs Never BF (ref) | OWOB* (OR [95% CI]) @ 12-21 y
| BF ≥9 mo vs Never BF (ref) | Note: this analysis is across 2 age groups
| BF ≥9 mo vs Never BF (ref) | In the full sample
| BF ≥9 mo vs Never BF (ref) | In males (N=830, 3142) | | 0.83 [0.67, 1.04]
| | In females (N=607, 3094) | 0.78 [0.64, 0.96]

a Abbreviations: %ile – percentile, ALSPAC – Avon Longitudinal Study of Parents and Children, Add Health – National Longitudinal Study of Adolescent Health, BF – breastfeeding/breastfed, CDS – Child Development Supplement of the Panel Study of Income Dynamics, CF – complementary feeding/complementary food, CI – confidence interval, CS – cross sectional, EBF – exclusive breastfeeding/exclusively breastfed, ECLS-B – Early Childhood Longitudinal Study-Birth, EDEN - Etude des Déterminants pré et post natals de la santé et du développement de l’Enfant, FBS – First Baby Study, FF – formula feeding/formula fed, Generation R – Generation Rotterdam, GROW – Growing Right Onto Wellness, GUS – Growing Up in Scotland, LCPUFA – Long-chain polyunsaturated fatty acid, MCS – Millennium Cohort Study, mo – months, NFP – Nurse-Family Partnership, NLSY79 – National Longitudinal Survey on Youth 1979 Cohort, NR – not reported, NRCT – non-randomized controlled trial, NS – nonsignificant, OB – obesity, OR – odds ratio, OW – overweight, OWOB – overweight and obesity, PC – prospective cohort study, PIAMA – Prevention and Incidence of Asthma and Mite Allergy, RC – retrospective cohort study, ref – reference, SE – standard error, UK – United Kingdom, U.S. – United States of America, WFL – weight-for-length, wk – weeks, y – years

b Exposures, from the articles included in the body of evidence, which address ever vs never consuming human milk, or vice versa

c Notations used for growth references: *CDC, †WHO, ‡IOTF, §Country-specific

d Anderson et al 2003 did not explicitly state that this finding was significant; however the text of the article implied that it was significant

Table 3 Risk of bias for the non-randomized controlled trial examining the relationship between ever vs never consuming human milk and overweight and obesity^a^,^b^

Study | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Outcome measurement | Missing data | Selection of the reported result
de Jong, 2011 ^7^ | Serious | Moderate | Low | Low | Moderate | Moderate | Low

a A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

b Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool (https://www.riskofbias.info/welcome/home/current-version-of-robins-i)” ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 4 Risk of bias for observational studies examining the relationship between ever vs never consuming human milk and overweight and obesity^a^,^b^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Outcome measurement | Missing outcome data | Selection of the reported result
Abraham, 2012 ^1^ | Serious | Moderate | Moderate | Low | Serious | Low | Low
Anderson, 2003 ^3^ | Serious | Serious | Serious | Low | Serious | Low | Low
Anderson, 2014 ^2^ | Serious | Serious | Serious | Low | Serious | Low | Low
Bjertnaes, 2019 ^4^ | Serious | Serious | Serious | Low | Serious | Low | Low
Bohr, 2015 ^5^ | Serious | Serious | Serious | Low | Serious | Serious | Low
Colen, 2014 ^6^ | Serious | Serious | Serious | Low | Serious | Low | Low
Durmus, 2011 ^9^ | Serious | Moderate | Moderate | Low | Serious | Moderate | Low
Durmus, 2014 ^8^ | Serious | Serious | Moderate | Low | Moderate | Moderate | Low
Evenhouse, 2005 ^10^ | Serious | Serious | Serious | Low | Serious | No information | Low
Feldman-Winter, 2018 ^11^ | Serious | Serious | Low | Low | Moderate | Moderate | Low
Hawkins, 2019 ^14^ | Serious | Serious | Low | Low | Moderate | Serious | Low
Heerman, 2019 ^15^ | Serious | Low | Moderate | Moderate | Moderate | Low | Low
Heppe, 2013 ^16^ | Serious | Serious | Serious | Low | Serious | Low | Low
Huang, 2014 ^17^ | Serious | Serious | Serious | Low | Serious | Low | Low
Layte, 2014 ^19^ | Serious | Serious | Moderate | Low | Moderate | Low | Low
Lee, 2019 ^20^ | Serious | Serious | Moderate | Low | Serious | Low | Low
Li, 2011 ^21^ | Serious | Serious | Serious | Low | Moderate | Low | Low
Lurbe, 2018 ^22^ | Serious | Serious | Serious | Low | Moderate | Low | Low
Massion, 2016 ^26^ | Serious | Moderate | Moderate | Low | Serious | Serious | Low
Metzger, 2009 ^27^ | Serious | Serious | Serious | Low | Moderate | Low | Low
Moschonis, 2017 ^30^ | Serious | No information | Moderate | Low | Serious | No information | Low
Moss, 2014 ^31^ | Serious | Moderate | Moderate | Low | Moderate | No information | Low
Nelson, 2005 ^32^ | Serious | Moderate | Serious | Low | Serious | Moderate | Low
Pattison, 2019 ^35^ | Serious | Moderate | Moderate | Low | Serious | Moderate | Low
Pluyman, 2018 ^36^ | Serious | Moderate | Moderate | Low | Moderate | Moderate | Low
Ruijsbroek, 2011 ^37^ | Serious | Low | Moderate | Low | Serious | Moderate | Low
Thorland, 2017 ^39^ | Serious | Serious | Serious | Low | Serious | Moderate | Low
van Rossem, 2011 ^40^ | Serious | Serious | Moderate | Low | Low | Serious | Low
Weng, 2013 ^41^ | Serious | Serious | Moderate | Low | Serious | Low | Low

a A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

b Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Duration of any human milk consumption among infants fed human milk

#### Description of the evidence examining the relationship between the duration of any human milk consumption, among infants fed human milk, and body composition, including obesity, from studies that conducted within-family comparisons of siblings (Table 5)

Four articles, published between 2005 and 2014, conducted within-family analyses comparing the duration of any human milk consumption between siblings and the siblings’ BMI, body fat percentage, or overweight and/or obesity status.^6,10,12,34^ The articles presented evidence from 4 independent cohorts from the United States (N=3) and Finland (N=1), described below.

1. Children of the National Longitudinal Survey on Youth 1979 Cohort (Children of NLSY79)
  Colen and Ramey^6^ examined a sample of children and adolescents whose mothers were part of the NLSY79 cohort from the United States. The study sample consisted of the subset of offspring who were singletons, born after the year 1978, and 4 to 14 years of age between 1986 and 2010. About 75% of participants were non-Hispanic white. Infant-feeding data were collected by maternal report at biannual survey rounds starting in 1986. The outcomes of interest were BMI and obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) at 4 to 14 years of age. Approximately 64% of height and weight data were collected by study staff, and the remainder were from maternal- or self-report. The authors conducted analyses on the full sample (N=8237), on a subsample consisting of participants with siblings in the study (N=7319), and on a second subsample consisting of siblings with discordant infant feeding (i.e., siblings fed differently during infancy; N=1773).
  - In the full sample and sibling subsample, there were small, but statistically significant, inverse associations between weeks of human milk consumption and BMI at 4 to 14 years (β = −0.007 ± 0.002 and β = −0.007 ± 0.003, respectively; p<0.01 for both). In the discordant sibling subsample, there was a small positive association that was nonsignificant (β = 0.005 ± 0.003).
  - Likewise, in the full sample and sibling subsample, there were small, but statistically significant, inverse associations between weeks of human milk consumption and obesity at 4 to 14 years (β = −0.007 ± 0.002, p<0.01 and β = −0.006 ± 0.002, p<0.05, respectively). In the discordant sibling subsample, there was no significant association (β = 0.001 ± 0.004).
2. National Longitudinal Study of Adolescent Health (Add Health)
  Evenhouse and Reilly^10^ studied the Add Health cohort from the United States. This cohort is a nationally representative sample of 10- to 18-year-olds in grades 7 to 12 during the 1994-1995 school year (baseline). Low-income, African-American, and Hispanic youth were oversampled. The duration of any human milk consumption (i.e., 0-3, 3-6, 6-9, 9-12, 12-24, or >24 months) among participants fed human milk (N=7417) was collected by parent recall at baseline. The outcomes of interest were BMI, overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) and obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) at 10 to 18 years of age. The method used to collect anthropometric data was not reported. The authors conducted analyses on the full sample, on a subsample consisting of participants with a sibling in the study (N=1607), and on a second subsample consisting of siblings with discordant infant feeding (i.e., siblings fed human milk for different durations; N=470).
  - In the full sample, sibling subsample, and discordant sibling subsample, there were no significant associations between the duration of any human milk consumption (as a quasi-continuous measure using the midpoints of the categorical durations) and BMI, overweight/obesity, or obesity at 10 to 18 years. The nonsignificant associations for the full sample and sibling subsample were small inverse associations (BMI β = −0.03 ± 0.006 and −0.03 ± 0.01, overweight/obesity OR = 0.98 ± 0.00 and 0.98 ± 0.01, obesity OR 0.98 ± 0.01 and 0.99 ± 0.01, respectively). The nonsignificant associations for the discordant sibling subsample were closer to the null or at the null (BMI β = 0.01 ± 0.03, overweight/obesity OR 1.01 ± 0.01, obesity OR 1.00 ± 0.02).
3. Growing Up Today Study (GUTS)
  Gillman et al^12^ examined a sample of children and adolescents in the U.S.-based GUTS cohort, whose mothers were part of the Nurses’ Health Study II. The study sample consisted of the subset of offspring who were (a) singletons, (b) born at 34 completed weeks of gestation or later, (c) 9 to 14 years of age at baseline, and (d) from sibships in which siblings shared the same biological father (based on maternal report of father’s height). Almost all participants were white (95%). Participants self-reported their height and weight at baseline, and infant-feeding data were collected by maternal recall a year later (when participants were 10 to 15 years of age). The authors assessed the association between the duration of human milk consumption and overweight/obesity (i.e., BMI ≥85^th^ percentile using CDC growth curves) at 9 to 14 years in the full sample of siblings (N=5614 participants from 2709 families), and the subsample of siblings with discordant infant feeding (i.e., siblings fed human milk for different durations, N=2372).
  - In the sample of siblings, each additional 3.7-month increase in the duration of any human milk consumption (i.e., the mean difference in duration for discordant siblings) was associated with significantly lower odds of overweight/obesity at 9 to 14 years when applying the same statistical adjustments for confounders as the discordant sibling analysis (i.e., age, sex, tanner stage, menarcheal status for girls, birthweight, birth order, inactivity, physical activity, and energy intake; OR [95% CI] = 0.88 [0.82, 0.94]). When the model was additionally adjusted for maternal BMI and smoking, and household income, the magnitude of the association was slightly attenuated and the confidence interval included the null (OR [95% CI] = 0.94 [0.88, 1.00]).
  - In the discordant sibling analysis, there was no significant association between consuming human milk for a duration longer than the mean family duration, compared with a duration shorter than the mean family duration, and odds of overweight/obesity at 9 to 14 years of age. The odds ratio was of similar magnitude to the odds ratios in the sibling analyses above, but the confidence interval was wider and included the null (OR [95% CI] = 0.92 [0.76, 1.11]).
4. Helsinki Birth Cohort
  O’Tierney et al^34^ studied the Helsinki Birth Cohort from Finland. Participants were born between 1934 and 1944 in Helsinki, Finland. The study sample consisted of members of the cohort who (a) were fed human milk, (b) had a sibling in the cohort, and (c) provided follow-up data in the year 2000, along with their sibling. Pediatric clinicians recorded infant feeding prospectively (participants had an average of 8 pediatric visits, which were free, from birth to 2 years of age). The outcomes of interest were BMI and overweight (i.e., BMI 25-30 kg/m^2^) from self-reported height and weight via questionnaire (N=831), and BMI and percent body fat from clinical measurement (N=129) at about 62 years of age. The analyses compared siblings with discordant infant feeding (i.e., siblings fed human milk for different durations).
  - There were no significant differences in BMI at about 62 years of age between participants fed human milk for <2, 3-4, 5-7 and ≥8 months. It may be important to note that when BMI was based on clinical measure (but not self-report) the quadratic trend approached significance (p=0.08). The U-shaped association between duration and BMI measured in the clinic is also somewhat evident from the following analyses. In comparison to a duration of 5 to 7 months, durations of <2 months and ≥8 months have nonsignificant associations with higher BMI:
    (a) <2 compared with 5-7 months: mean difference 2.3 kg/m^2^ [95% CI −0.1, 4.7] for clinical measure (0.3 [−0.5, 1.1] for self-report)
    (b) 3-4 compared with 5-7 months: mean difference −0.4 kg/m^2^ [95% CI −2.7, 1.8] for clinical measure (0.3 [−0.5, 1.1] for self-report)
    (c) ≥8 compared with 5-7 months: mean difference 1.2 kg/m^2^ [95% CI −0.9, 3.2] for clinical measure (0.2 [−0.5, 1.0] for self-report)
  - There were no significant differences in the percent of participants who were overweight at about 62 years of age between participants fed human milk for <2, 3-4, 5-7 and ≥8 months. Likewise, there were no significant differences in the percent of participants who were overweight between participants fed human milk for:
    (a) <2 compared with 5-7 months: mean difference 1.6% [95% CI −7.7, 11.0]
    (b) 3-4 compared with 5-7 months: mean difference 1.9% [95% CI −8.0, 11.8]
    (c) ≥8 compared with 5-7 months: mean difference 8.8% [95% CI −0.3, 18.0]
  - There was a significant quadratic trend (p=0.03) in the percent body fat of participants fed human milk for <2, 3-4, 5-7 and ≥8 months. The U-shaped association between duration and percent body fat is also evident from the following analyses:
    (a) <2 compared with 5-7 months: mean difference 3.9% [95% CI 0.3, 7.4]; p<0.05
    (b) 3-4 compared with 5-7 months: mean difference 0.3% [95% CI −3.1, 3.7]
    (c) ≥8 compared with 5-7 months: mean difference 1.3% [95% CI −1.7, 4.3]

Table 5 Evidence examining the relationship between the duration of any human milk consumption, among infants fed human milk, and body composition, including obesity, from studies that conducted within-family comparisons of siblings^a^

Article; Study design (Study name); Country | Duration of any human milk exposure^b^ | Outcome^c^ | Significant findings | Nonsignificant findings
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | BMI (β ± SE, kg/m2) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | In the full sample (N=8,237) | −0.007 ± 0.002; p<0.01
| | In the subsample of siblings (N=7,319) | −0.007 ± 0.003; p<0.01
| | In the subsample of siblings with discordant exposures (N=1,773) | | 0.005 ± 0.003; NS
| | OB* (β ± SE) @ 4-14 y
| | In the full sample (N=8,237) | −0.007 ± 0.002; p<0.01
| | In the subsample of siblings (N=7,319) | −0.006 ± 0.002; p <0.05
| | In the subsample of siblings with discordant exposures (N=1,773) | | 0.001 ± 0.004; NS
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | BMI (β ± SE, kg/m2) @ 10-18 y
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | In the full sample (N=7417) | | −0.03 ± 0.006; p<0.10
| | In the subsample of siblings (N=1607) | | −0.03 ± 0.01; p<0.10
| | In the subsample of siblings with discordant exposures (N=470) | | 0.01 ± 0.03; NS
| | OWOB* (OR ± SE from logit) @ 10-18 y
| | In the full sample (N=7417) | | 0.98 ± 0.00; p<0.10
| | In the subsample of siblings (N=1607) | | 0.98 ± 0.01; p<0.10
| | In the subsample of siblings with discordant exposures (N=470) | | 1.01 ± 0.01; NS
| | OB* (OR ± SE from logit) @ 10-18 y
| | In the full sample (N=7417) | | 0.98 ± 0.01; p<0.10
| | In the subsample of siblings (N=1607) | | 0.99 ± 0.01; NS
| | In the subsample of siblings with discordant exposures (N=470) | | 1.00 ± 0.02; NS
Gillman 2006 ^12^; CS (GUTS); U.S. | BF duration (per 3.7 mo, which was the mean difference in BF duration for discordant siblings) | OWOB* (OR [95% CI]) @ 9-14 y in the sample of siblings (N=5614) | 0.88 [0.82, 0.94]; (Adjusted for same confounders as discordant sibling analysis) | 0.94 [0.88, 1.00]; (Also adjusted for maternal BMI and smoking, household income)
| BF longer than the mean duration of his/her participating sibship vs shorter | BF OWOB* (OR [95% CI]) @ 9-14 y in the subsample of siblings with discordant exposures (N=2372) | | 0.92 [0.76, 1.11]
O’Tierney 2009 ^34^; PC (Helsinki Birth Cohort); Finland | Trend across the BF duration categories <2, 3-4, 5-7, ≥8 mo | BMI (mean ± SD, kg/m2) at ~62 y in the sample of siblings with discordant exposures
O’Tierney 2009 ^34^; PC (Helsinki Birth Cohort); Finland | Trend across the BF duration categories <2, 3-4, 5-7, ≥8 mo | from self-reported height and weight (N=206, 168, 233, 224) | | 26.6 ± 4.3 vs 26.3 ± 4.3 vs 26.2 ± 4.2 vs 26.5 ± 4.0; p=0.80 (linear), 0.90 (quadratic)
| | from clinical measurement (N=22, 30, 38, 39) | | 29.5 ± 4.3 vs 26.8 ± 5.2 vs 26.9 ± 4.2 vs 28.2 ± 4.9; p=0.80 (linear), 0.08 (quadratic)
| | OW (% BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=206, 168, 233, 224) | | 42.7 vs 42.9 vs 41.2 vs 50.0; p=0.08 (linear), 0.50 (quadratic)
| | %FM (mean ± SD, %) at ~62 y in a sibling sample (N=21, 26, 36, 38) | 32.6 ± 9.7 vs 27.6 ± 8.5 vs 28.4 ± 6.6 vs 30.8 ± 8.0; p=0.03 (quadratic) | p=0.50 (linear)
| BF <2 mo vs BF 5-7 mo (ref) | BMI (mean difference [95% CI], kg/m2) at ~62 y in a sample of siblings with discordant exposures
| BF <2 mo vs BF 5-7 mo (ref) | from self-reported height and weight (N=206, 233) | | 0.3 [−0.5, 1.1]
| | from clinical measurement (N=22, 38) | | 2.3 [−0.1, 4.7]
| | OW (difference, % BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=206, 233) | | 1.6 [−7.7, 11.0]
| | %FM (difference, %) at ~62 y in a sample of siblings with discordant exposures (N=21, 36) | 3.9 [0.3, 7.4]
| BF 3-4 mo vs BF 5-7 mo (ref) | BMI (mean difference [95% CI], kg/m2) at ~62 y in a sample of siblings with discordant exposures
| BF 3-4 mo vs BF 5-7 mo (ref) | from self-reported height and weight (N=168, 233) | | 0.3 [−0.5, 1.1]
| | from clinical measurement (N=30, 38) | | −0.4 [−2.7, 1.8]
| | OW (difference, % BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=168, 233) | | 1.9 [−8.0, 11.8]
| | %FM (difference, %) at ~62 y in a sample of siblings with discordant exposures (N=26, 36) | | 0.3 [−3.1, 3.7]
| BF ≥8 mo vs BF 5-7 mo (ref) | BMI (mean difference [95% CI], kg/m2) at ~62 y in a sample of siblings with discordant exposures
| BF ≥8 mo vs BF 5-7 mo (ref) | from self-reported height and weight (N=224, 233) | | 0.2 [−0.5, 1.0]
| | from clinical measurement (N=39, 38) | | 1.2 [−0.9, 3.2]
| | OW (difference, % BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=224, 233) | | 8.8 [−0.3, 18.0]
| | %FM (difference, %) at ~62 y in a sample of siblings with discordant exposures (N=38, 36) | | 1.3 [−1.7, 4.3]

a Abbreviations: %FM – percent fat mass, Add Health – National Longitudinal Study of Adolescent Health, BF – breastfeeding/breastfed, BMI – body mass index, CI – confidence interval, CS – cross sectional, GUTS – Growing Up Today Study, mo – months, NLSY79 – National Longitudinal Survey on Youth 1979 Cohort, NS – nonsignificant, OB – obesity, OR – odds ratio, OWOB – overweight and obesity, PC – prospective cohort study, ref – reference, SE – standard error, U.S. – United States of America, wk – weeks, y – years

b Exposures, from the articles included in the body of evidence, which address the duration of any human milk consumption among infants fed human milk

c Notations used for growth references: *CDC, †WHO, ‡IOTF, §Country-specific

#### Description of the evidence examining the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity at 2 years of age and older (Table 6)

Twenty-one articles, published between 2005 and 2019, were identified that met the inclusion criteria and examined the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity. ^4,6,8–10,12,13,15,18,23–26,28–30,33,34,37,38,42^ They presented evidence from 19 independent studies. Four of the 19 studies were also described in the section about evidence from siblings. ^6,10,12,34^ A description of the studies is presented below by age group (i.e., 2 to 5 years, 6 to 11 years, 12 to 19 years, and 20 years and older).

##### Studies with evidence in multiple age groups

1 Generation Rotterdam (Generation R) Study
  Durmus et al (2011)^9^ and Durmus et al (2014)^8^ presented evidence from the Generation R Study, which was a prospective cohort study conducted in the Netherlands. Both samples consisted of singleton infants who had available information on infant feeding. Durmus et al (2011)^9^ examined dichotomous comparisons of 0-3 months and 3-6 months of human milk consumption with >6 months of human milk consumption. Durmus et al (2014)^8^ examined dichotomous comparisons of >0-1.99, 2-3.00, and 4-5.99 months of human milk consumption with ≥6 months of human milk consumption, and also examined the trend across the 4 duration categories. Infant-feeding data were obtained from clinical delivery reports at birth and by maternal report at 2, 6, and 12 months of age. The outcome of interest in both articles was overweight and obesity (combined).
  - Durmus et al (2011)^9^ found significant inverse associations between the duration of any human milk consumption and odds of overweight/obesity at 2, but not at 3 years of age. Consuming human milk for shorter durations of 0-3 months or 3-6 months, in comparison to a longer duration of >6 months, was associated with significantly higher odds of overweight/obesity at 2 years (OR [95% CI] ~2 [~1.5, ~3], p<0.01 and ~2 [~1, ~3], p<0.05, respectively). However, at 3 years, the associations were nonsignificant and slightly below the null (OR [95% CI] ~0.9 [~0.8, ~2] and ~0.8 [~0.7, ~2], respectively).
  - Durmus et al (2014)^8^ found some significant positive associations between the duration of any human milk consumption and odds of overweight/obesity at 6 years of age. There was a significant trend across 4 duration categories (>0-1.9, 2-3.9, 4-5.9, and ≥6 months). In addition, consuming human milk for the shorter duration of >0-1.9 months, in comparison to the longer duration of ≥6 months, was associated with significantly lower odds of overweight/obesity at 6 years of age (OR ~0.7 with the top error bar just below 1.0). However, the association was nonsignificant when durations of 2-3.9 and 4-5.9 months were compared with ≥6 months (OR [95% CI] ~0.8 [~0.7, ~1.1] and ~1.0 [~0.8, ~1.3], respectively).
2 Moschonis et al^30^ presented analyses of 4 European cohorts: Avon Longitudinal Study of Parents and Children (ALSPAC), Etude des Déterminants pré et post natals de la santé et du développement de l’Enfant (EDEN), EuroPrevall, and Generation XXI, conducted in the United Kingdom, France, Greece, and Portugal, respectively. Infant-feeding data were collected by parent report via questionnaire at 6 and 15 months of age in ALSPAC, at 4, 8, and 12 months of age in EDEN, at 15 months of age in Generation XXI, and at 12, 24, and 30 months of age in EuroPrevall. The authors examined dichotomous comparisons of <1 month, 1-3 months, and 3-6 months, compared with ≥6 months of human milk consumption. Height and weight were measured at each study site and used to identify participants who were overweight and obese (combined, using IOTF cutoffs) at 4 (N=6522), 9 (N=7540), and 13 years of age (N=6124) in the ALSPAC cohort, at 4 years of age in the EuroPrevall (N=309) and Generation XXI (N=3387) cohorts, and at 5 years of age (N=1070) in EDEN cohort.
  - In the ALSPAC cohort, consuming human milk for 3-6 months, compared with ≥6 months, was associated with significantly lower odds of overweight/obesity at 4 and at 13 years of age (ORs ~0.7, p=0.008, and ~0.8, p=0.031, respectively; CIs not reported), but not at 9 years of age (OR ~1.1, CI not reported). There were no significant associations between consuming human milk for <1 or 1-3 months, compared with ≥6 months, and overweight/obesity at 4, 9, or 13 years of age in the ALSPAC cohort (ORs ~1.0 and ~0.9, respectively, at 4 years of age, ~1.1 and ~1.1, respectively, at 9 years of age, and ~1.3 and ~1.0, respectively, at 13 years of age).
  - In the EuroPrevall and Generation XXI cohorts, there were no significant associations between consuming human milk for <1, 1-3, or 3-6 months, compared with ≥6 months, and the odds of overweight/obesity at 4 years of age (OR ~0.6, ~0.7, and ~1.3, respectively, in the EuroPrevall cohort and ~0.9, ~1.0, and ~1.1, respectively, in the Generation XXI cohort; CIs not reported). Likewise, in the EDEN cohort, there were no significant associations between consuming human milk for <1, 1-3, or 3-6 months, compared with ≥6 months, and the odds of overweight/obesity at 5 years of age (OR ~0.8, ~0.8, and ~0.6, respectively; CIs not reported).
3 Promotion of Breastfeeding Intervention Trial (PROBIT)
  Martin et al (2013)^25^ and Martin et al (2017)^24^ presented evidence from the PROBIT study conducted in Belarus. This was a cluster randomized controlled trial of an intervention to promote prolonged duration and exclusivity of human milk feeding among mothers who chose to feed human milk. The study enrolled 17,046 infants at birth and followed 13,879 children to 11.5 years of age^25^ and 13,557 adolescents to 16 years of age^24^. Study pediatricians collected human milk-feeding data at well-baby medical appointments, and the intervention group had higher rates of any human milk consumption measured at 3, 6, 9, and 12 months. The outcomes, overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) and obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves), were secondary outcomes of the study^iii^ and were measured by study staff. The authors used an intention-to-treat analysis that compared the intervention group with the control group.
  - At 11.5 years of age, the intervention group had significantly higher odds of overweight/obesity (compared with BMI <85^th^ percentile) than the control group (OR 1.18 [95% CI: 1.01, 1.39]). The odds of obesity (also compared with BMI <85^th^ percentile) were similar, but the confidence interval was wider and included the null (OR 1.17 [0.97, 1.41]).
  - Likewise, at 16 years of age, the intervention group had significantly higher odds of overweight/obesity (compared with BMI <85^th^ percentile) than the control group (OR 1.14 [95% CI: 1.02, 1.28]). The odds of obesity (in contrast to the 11.5 year analysis, this was compared with BMI <95^th^ percentile) were slightly lower and had a wider confidence interval that included the null (OR 1.09 [0.92, 1.29]).
4 Prevention and Incidence of Asthma and Mite Allergy (PIAMA)
  Ruijsbroek et al^37^ presented evidence from the PIAMA study in the Netherlands, which was a birth cohort study and prospective follow-up of (1) participants in an intervention study of mite-impermeable mattress and pillow covers, and (2) participants in a natural-history study in which no intervention was applied. The sample for the intervention arm of the study consisted of children of allergic mothers (mothers with at least 1 of the following: asthma ever, pet allergy, house dust mite allergy or nasal allergy such as hay fever). The sample for the natural-history study consisted of children born to both allergic and non-allergic mothers. The authors examined consuming human milk for 1-16 weeks, compared with >16 weeks, as a dichotomous variable. Infant-feeding data were collected prospectively by parental report at 3 and 12 months of age. The outcomes of interest were overweight and obesity (combined) and obesity, defined using IOTF cut-offs, at 3 to 8 years of age (N=3963). Anthropometric data were collected via parental recall (based on doctor or nurse report if measured within the last 3 months, or measured by parents), but specific methods were not reported.
  - There was a significant association between consuming human milk for 1-16 weeks, compared with >16 weeks, and higher odds of obesity at 3 to 8 years of age (OR 1.81 [95% CI 1.07, 3.04]). The odds of overweight/obesity were in the same direction but were not statistically significant (OR 1.25 [95% CI 0.98, 1.59]).
5 Children of the National Longitudinal Survey on Youth 1979 Cohort (Children of NLSY79)
  Colen and Ramey^6^ examined a sample of children and adolescents whose mothers were part of the National Longitudinal Survey on Youth 1979 Cohort from the United States. The study sample consisted of the subset of offspring who were singletons, born after the year 1978, and 4 to 14 years of age between 1986 and 2010. About 75% of participants were non-Hispanic white. Infant-feeding data were collected by maternal report at biannual survey rounds starting in 1986. The outcome of interest was obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) at 4 to 14 years of age. Approximately 64% of height and weight data were from measurements by study staff, and the remainder were from maternal- or self-report. The authors conducted analyses on the full sample (N=8237), on a subsample consisting of participants with siblings in the study (N=7319), and on a second subsample consisting of siblings with discordant infant feeding (i.e., siblings fed differently during infancy; N=1773).
  - In the full sample and sibling subsample, there were small, but statistically significant, inverse associations between weeks of human milk consumption and obesity at 4 to 14 years (β = −0.007 ± 0.002, p<0.01 and β = −0.006 ± 0.002, p<0.05, respectively). In the discordant sibling subsample, there was no significant association (β = 0.001 ± 0.004).
6 National Longitudinal Study of Adolescent Health (Add Health)
  Evenhouse and Reilly^10^ studied the Add Health cohort from the United States. This cohort is a nationally representative sample of 10- to 18-year-olds in grades 7 to 12 during the 1994-1995 school year (baseline). Low-income, African-American, and Hispanic youth were oversampled. The duration of any human milk consumption (i.e., 0-3, 3-6, 6-9, 9-12, 12-24, or >24 months) among participants fed human milk (N=7417) was collected by parent recall at baseline. The outcomes of interest were overweight/obesity (i.e., BMI ≥85^th^ percentile based on CDC growth curves) and obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) at 10 to 18 years of age. The method used to collect anthropometric data was not reported. The authors conducted analyses on the full sample, on a subsample consisting of participants with a sibling in the study (N=1607), and on a second subsample consisting of siblings with discordant infant feeding (i.e., siblings fed human milk for different durations; N=470).
  - In the full sample, sibling subsample, and discordant sibling subsample, there were no significant associations between the duration of any human milk consumption (as a quasi-continuous measure using the midpoints of the categorical durations) and overweight/obesity or obesity at 10 to 18 years. The nonsignificant associations for the full sample and sibling subsample were small inverse associations (overweight/obesity OR = 0.98 ± 0.00 and 0.98 ± 0.01, obesity OR 0.98 ± 0.01 and 0.99 ± 0.01, respectively). The nonsignificant associations for the discordant sibling subsample were closer to the null or at the null (overweight/obesity OR 1.01 ± 0.01, obesity OR 1.00 ± 0.02).
7 Growing Up Today Study (GUTS)
  Gillman et al^12^ examined a sample of children and adolescents in the U.S.-based GUTS cohort, whose mothers were part of the Nurses’ Health Study II. The study sample consisted of the subset of offspring who were (a) singletons, (b) born at 34 completed weeks of gestation or later, (c) 9 to 14 years of age at baseline, and (d) from sibships in which siblings shared the same biological father (based on maternal report of father’s height). Almost all participants were white (95%). Participants self-reported their height and weight at baseline, and infant-feeding data were collected by maternal recall a year later (when participants were 10 to 15 years of age). The authors assessed the association between the duration of human milk consumption and overweight/obesity (i.e., BMI ≥85^th^ percentile using CDC growth curves) at 9 to 14 years in the full sample of siblings (N=5614 participants from 2709 families), and the subsample of siblings with discordant infant feeding (i.e., siblings fed human milk for different durations, N=2372).
  - In the sample of siblings, each additional 3.7-month increase in the duration of any human milk consumption (i.e., the mean difference in duration for discordant siblings) was associated with significantly lower odds of overweight/obesity at 9 to 14 years when applying the same statistical adjustments for confounders as the discordant sibling analysis (i.e., age, sex, tanner stage, menarcheal status for girls, birthweight, birth order, inactivity, physical activity, and energy intake; OR [95% CI] = 0.88 [0.82, 0.94]). When the model was additionally adjusted for maternal BMI and smoking, and household income, the magnitude of the association was slightly attenuated and the confidence interval included the null (OR [95% CI] = 0.94 [0.88, 1.00]).
  - In the discordant sibling analysis, there was no significant association between consuming human milk for a duration longer than the mean family duration, compared with a duration shorter than the mean family duration, and odds of overweight/obesity at 9 to 14 years of age. The odds ratio was of similar magnitude to the odds ratios in the sibling analyses above, but the confidence interval was wider and included the null (OR [95% CI] = 0.92 [0.76, 1.11]).
8 Child Development Supplement of the Panel Study of Income Dynamics (CDS)
  Jiang and Foster^18^ examined a sample of randomly-selected children born between 1984 and 1997 from the U.S.-based CDS. The sample was 47% white, 40% black, and 13% of of other racial or ethnic backgrounds. The authors examined the number of months participants consumed human milk as a continuous variable, which was truncated at 12 months for those who consumed human milk beyond the first year (N=268). Infant-feeding data were reported by mothers in 1997 when participants were between 4 months and 13 years of age. The outcome of interest was obesity at 5 to 18 years of age (i.e., BMI ≥95^th^ percentile based on CDC growth curves; N=1512). Height and weight were measured by study staff for 99% of participants using methods that were not reported. For the remaining 1% of participants, height and weight were reported by parents from participants’ last doctor’s visit.
  - There was no significant association between the number of months participants consumed human milk and obesity at 5-18 years of age (data not reported).

##### Studies with evidence from 2 to 5 years of age

Colen and Ramey^6^: See number 5, above

Durmus et al (2011)^9^: See number 1, above

9 Child, Parents, and Health: Lifestyle and Genetic Constitution (KOALA)
  Gubbels et al^13^ assessed participants in the prospective KOALA birth cohort study from the Netherlands. The sample consisted of infants born to mothers with “conventional lifestyles” (about 83% of the baseline sample) and “alternative lifestyles” with regard to child-rearing practices, dietary habits (e.g., organic, vegetarian), vaccination schemes, and/or use of antibiotics. Infant-feeding data were collected by parent report via questionnaires at 3, 7, and 12 months of age, and the authors examined the duration of any human milk consumption, in months, as a continuous variable. Height and weight data were also reported by parents when participants were 2 and 4 years of age. The outcome of interest was overweight/obesity (combined; i.e., BMI z-score ≥85^th^ percentile according to a national reference).
  - There was no association between the number of months participants consumed human milk and the odds of overweight/obesity at 2 or 4 years of age (i.e., the odds were at the null; OR [95% CI] 1.01 [0.97, 1.05] and 1.00 [0.96, 1.05], respectively).

Jiang and Foster^18^: See number 8, above

10 Steps to Healthy Development (STEPS)
  Makela et al^23^ examined participants in the STEPS study, a prospective cohort study conducted in Finland. The sample was 100% Finnish. Infant-feeding data were reported prospectively by parents using a diary, and the study authors assessed the duration of any human milk consumption, in months, as a continuous variable. Health-care professionals measured weight and length (<24 months) or height (>24 months) of participants and identified individuals who were overweight or obese at 2 years of age by plotting BMI on national growth references.
  - There was no significant association between the number of months participants consumed human milk and the odds of overweight or obesity at 2 years of age (OR 0.96, p=0.157 and 0.93, p=0.141, respectively; CIs not reported).
11 Oregon Pregnancy Risk Assessment Monitoring System (Oregon PRAMS)
  Modrek et al^28^ assessed data collected through Oregon PRAMS, a state-based data collection initiative of the Centers for Disease Control and Prevention in the United States. The sample was born in 2009, and had mothers (selected via PRAMS by stratified random sampling of birth certificates) who completed PRAMS surveys when their child was 2 to 6 months and 2 years of age. Oregon oversampled mothers from racial and ethnic minorities; however the sample was still predominantly non-Hispanic white (i.e., 76% of mothers; child race and ethnicity were not reported). The exposure of interest was the duration of any human milk consumption, in weeks, as a continuous variable. The authors used an instrumental variable analysis that used variation on whether a mother fed human milk to her infant exclusively in the hospital after birth (data collected at the first survey) as an instrumental variable to examine the relationship between the duration of any human milk consumption (data collected in the second survey) and the outcome of interest. The outcomes of interest were overweight at 2 years of age and obesity at 2 years of age, applying IOTF thresholds. Weight and height at 2 years of age were reported by mothers during the second survey.
  - There was a significant inverse association between the duration of any human milk consumption and obesity at 2 years of age (instrumental variable estimate −0.0082 [SE −0.018, −0.001]; p<0.05). The association with overweight was similar but was not statistically significant (instrumental variable estimate −0.008 [SE −0.024, 0.004]; p<0.1).

Moschonis et al^30^: See number 2, above

Ruijsbroek et al^37^: See number 4, above

12 Alaska Pregnancy Risk Assessment Monitoring System (Alaska PRAMS)
  Wojcicki et al^42^ assessed data collected through Alaska PRAMS. The sample was born in 2005-2006, and had mothers (selected via PRAMS by stratified random sampling of birth certificates) who completed PRAMS surveys when their children were 2 to 6 months and 3 years of age. Alaska conducted stratification according to maternal Alaska Native race and infant birth weight. The exposure of interest was the duration of any human milk consumption, in months, as a continuous variable. Weight and height at 3 years of age were reported by mothers during the second survey. The outcome of interest was obesity at 3 years of age (i.e., BMI ≥95^th^ percentile; the growth reference used was not reported). The authors conducted analyses in Alaska non-Native (N=474) and Alaska Native (N=226) children.
  - In Alaska non-Native participants, there was a significant inverse association between the number of months of human milk consumption and odds of obesity at 3 years of age (OR 0.95 [95% CI 0.91, 0.995], p=0.03).
  - In Alaska Native participants, the association was attenuated and nonsignificant (OR 0.99 [95% CI 0.96, 1.02], p=0.44).

##### Studies with evidence from 6 to 11 years of age

13 Bjertnaes et al^4^ examined a sample of children enrolled in a prospective cohort study conducted in Norway (no cohort name provided). Children included in the cohort started school in Oppland County, a predominantly rural county, in 2007. The authors examined the number of months participants consumed human milk as a continuous variable. Infant-feeding data were recalled by parents at routine school entry health assessments when children were 5-6 years of age. The outcome of interest was overweight/obesity (combined) at approximately 8 years of age (N=951) using BMI cut-offs provided by the IOTF. Height and weight were measured by school nurses, but specific methods were not reported.
  - There was no significant association between the number of months participants consumed human milk and the odds of overweight/obesity at 8 years of age (OR 1.02 [95% CI 0.99, 1.06], p=0.25)

Colen and Ramey^6^: See number 5, above

Durmus et al (2014)^8^: See number 1, above

Evenhouse and Reilly^10^: See number 6, above

Gillman et al^12^: See number 7, above

14 Growing Right Onto Wellness (GROW)
  Heerman et al^15^ examined data from a prospective cohort from the GROW study conducted in the United States. Participants were from low-income families (e.g., 100% qualified for services for underserved populations such as Medicaid or WIC, 43% were food insecure), mostly Hispanic (i.e., 63% Hispanic Mexican, 28% Hispanic non-Mexican, 9% non-Hispanic), and considered to be at high risk for developing obesity at baseline when they were 3 to 5 years of age (i.e., BMI ≥50^th^ and <95^th^ percentile based on CDC growth curves). Infant-feeding data were collected by parent recall at baseline, and the authors examined a dichotomous comparison of <6 months with ≥6 months of human milk consumption. Trained study staff measured height and weight. The outcome of interest was obesity (i.e., BMI ≥95^th^ percentile based on CDC growth curves) when participants were a mean of about 7 years of age.
  - In this high-risk U.S. cohort, there was no significant association between consuming human milk for <6 months, compared with ≥6 months, and the odds of obesity at about 7 years of age (OR 0.72 [95% CI 0.46, 1.14]).

Jiang and Foster^18^: See number 8, above

Martin et al (2013)^25^: See number 3, above

15 Millennium Cohort Study (MCS)
  Massion et al^26^ examined samples of children who participated in the MCS, a nationally representative sample of children born in the United Kingdom between September 2000 and January 2002. Children living in disadvantaged areas and ethnic minorities were oversampled to adequately represent hard-to-reach populations. The authors examined consuming human milk for <4 months, compared with >4 months, as a dichotomous variable. Infant-feeding data were obtained by parent report at the first interview when infants were between 6 and 12 months of age (mean age of 9.2 months). The outcome of interest was overweight and obesity (combined; defined using IOTF cutoffs) at 11 years of age (N=11,764). Children’s heights and weights were measured by trained research staff using standardized protocols.
  - The authors reported no significant association between consuming human milk for <4 months, compared with >4 months, and the relative risk of overweight/obesity at 11 years of age (RR ~1.1 [95% CI ~0.9, ~1.2]).
16 Danish National Birth Cohort (DNBC)
  Morgen et al^29^ examined a sample from the DNBC. Participants were born full term between 1996 and 2002, and did not have any siblings in the cohort. Infant-feeding data were reported prospectively by mothers during interviews at 6 and 18 months of infant age. The number of weeks infants consumed human milk was assessed using dichotomous comparisons of 20.0-31.9 weeks and 32.0-39.9 weeks with ≥40 weeks. At 7 years of age, height and weight were measured and reported by mothers for the majority of participants (67%) or by school doctors, public-health nurses, or general practitioners. Values reported by mothers were compared with values measured by school doctors or public-health nurses for a subgroup of participants (N=1122), and the study authors found no systematic differences. At 11 years of age, height and weight were only reported by parents. The outcome of interest was overweight/obesity (based on IOTF references) as a dichotomous variable at 7 and 11 years of age.
  - There was a significant association between consuming human milk for 20.0-31.9 weeks, compared with ≥40 weeks, and lower odds of overweight/obesity at both 7 and 11 years of age (OR [95% CI] 0.77 [0.64, 0.93], p=0.006 and 0.58 [0.43, 0.78], p<0.0001, respectively).
  - The associations between consuming human milk for 32.0-39.9 weeks, compared with ≥40 weeks, and odds of overweight/obesity at 7 and 11 years of age were in the same direction, but were attenuated and no longer statistically significant (OR [95% CI] 0.86 [0.73, 1.01], p=0.7 and 0.82 [0.64, 1.04], p=0.1, respectively).

Moschonis et al^30^: See number 2, above

17 Medio Ambiente y Lactancia Materna (MALAMA)
  Ortega-Garcia et al^33^ presented evidence from the MALAMA study in Spain. Participants were born full term (i.e., gestational age >37 weeks) with a birthweight >2500g, had 1- and 5-minute Apgar scores of ≥7 and ≥8, respectively, and had infant-feeding and anthropometric data for the analyses (N=231). Infant-feeding data were reported prospectively by parents during interviews with trained nurses at birth and at 1, 3, 6, and 12 months of infant age. The study examined the number of weeks infants consumed any human milk as a continuous variable. Weight and height at 6 years of age were measured by pediatricians during well-child primary care visits, and the authors assessed overweight/obesity (i.e., BMI >1 SD based on WHO growth curves) at 6 years of age.
  - The authors found no significant association between the number of weeks participants consumed human milk and overweight/obesity at 6 years of age (β=0.015 [95% CI −0.003, 0.032], p=0.11).

Ruijsbroek et al^37^: see number 4, above

18 Skledar and Milosevic^38^ conducted a retrospective cohort study of Caucasian children who were in their first year of primary school in Croatia between 2002 and 2006. All children in the cohort were born full term (i.e., 37 to 42 weeks gestational age), and had complete data on infant feeding, anthropometry, and the confounding variables used in the analyses (N=302). Infant-feeding data, height, and weight were recorded in medical charts prospectively by primary care providers and obtained retrospectively for the study from a medical chart review. The authors examined the number of months infants consumed any human milk as a continuous variable, and the odds of overweight/obesity at 6 to 7 years of age (i.e., BMI ≥85^th^ percentile based on CDC growth curves).
  - There was a nonsignificant positive association between the number of months participants consumed human milk and the odds of overweight/obesity at 6 to 7 years of age; the wide confidence interval included the null (OR 1.45 [95% CI 0.95, 2.20], p=0.080).

##### Studies with evidence from 12 to 19 years of age

Colen and Ramey^6^: See number 5, above

Evenhouse and Reilly^10^: See number 6, above

Gillman et al^12^: See number 7, above

Jiang and Foster^18^: See number 8, above

Martin et al (2017)^24^: See number 3, above

Moschonis et al^30^: See number 2, above

##### Studies with evidence at 20 years of age and older

19 Helsinki Birth Cohort
  O’Tierney et al^34^ studied the Helsinki Birth Cohort from Finland. Participants were born between 1934 and 1944 in Helsinki, Finland. The study sample consisted of members of the cohort who (a) were fed human milk, (b) had a sibling in the cohort, and (c) provided follow-up data in the year 2000, along with their sibling. Pediatric clinicians recorded infant feeding prospectively (participants had an average of 8 pediatric visits, which were free, from birth to 2 years of age). The outcome of interest was overweight (i.e., BMI 25-30 kg/m^2^) from self-reported height and weight via questionnaire (N=831) at about 62 years of age. The analyses compared siblings with discordant infant feeding (i.e., siblings fed human milk for different durations).
  - There were no significant differences in the percent of participants who were overweight at about 62 years of age between participants fed human milk for <2, 3-4, 5-7 and ≥8 months. Likewise, there were no significant differences in the percent of participants who were overweight between participants fed human milk for:
    (a) <2 compared with 5-7 months: mean difference 1.6% [95% CI −7.7, 11.0]
    (b) 3-4 compared with 5-7 months: mean difference 1.9% [95% CI −8.0, 11.8]
    (c) ≥8 compared with 5-7 months: mean difference 8.8% [95% CI −0.3, 18.0]

#### Synthesis and assessment^iv^ of the evidence examining the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity at 2 years of age and older (Table 6)

Twenty-one articles presented evidence from 19 independent studies about the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity at 2 years of age and older.^4,6,8–10,12,13,15,18,23–26,28–30,33,34,37,38,42^ A synthesis and assessment of the evidence follows.

##### Consistency

Nine of the 19 studies (11 of 21 articles) found significant associations between the duration of any human milk consumption and overweight and/or obesity. The significant associations were inconsistent in direction:

- Five of the 9 studies found significant inverse associations between the duration of human milk consumption and overweight/obesity at 2 years of age,^28^ 3 years of age,^42^ 3 to 8 years of age,^37^ 4 to 14 years of age,^6^ and 9 to 14 years of age.^12^ Four of these studies were from the United States^6,12,28,42^ and 1 was from the Netherlands.^37^
- Three of the 9 studies found significant positive associations between the duration of human milk consumption and overweight/obesity at 4 and 13 years of age,^30^ 7 and 11 years of age,^29^ and 11.5 and 16 years of age.^24,25^ All 3 studies were from Europe (Belarus, Denmark, and the U.K. arm of a multi-cohort study).
- The last of the 9 studies, also from Europe (the Netherlands), reported significant associations, but in opposite directions, in different articles.^8,9^ Shorter, compared with longer, durations of human milk consumption were associated with higher risk of overweight/obesity at 2 years of age and lower risk of overweight/obesity at 6 years of age.

The remaining 10 studies found no significant associations between the duration of any human milk consumption and overweight and/or obesity at ages between 2 and 62 years of age.^4,10,13,15,18,23,26,33,34,38^

Five studies were of particular interest because they used analyses intended to help address bias from confounding, which may pervade infant-feeding research (see Risk of Bias, below). One study was a cluster randomized trial to promote prolonged duration and exclusivity of human milk feeding, which resulted in an intervention group with significantly higher rates of any human milk consumption measured at 3, 6, 9, and 12 months of age. Study authors, therefore, were able to conduct intention-to-treat analyses of the intervention versus control group to examine the effect of the intervention on overweight/obesity and obesity.^24,25^ There were also 4 observational studies that conducted within-family analyses of siblings fed differently in infancy, reducing confounding from genetic and environmental factors that siblings share.^6,10,12,34^ The evidence from these 5 studies was also inconsistent:

- The intention-to-treat analyses found that the intervention group had a higher risk of overweight and/or obesity at 11.5 and 16 years of age.^24,25^
- None of the within-family analyses of siblings found significant associations between the duration of any human milk consumption and risk of overweight and/or obesity; point estimates were at or close to the null.
- We also examined BMI in 2 studies that had both full-sample and within-family analyses.^6,10^ One study did not find significant associations between the duration of human milk consumption and BMI at 10 to 18 years of age in either analysis.^10^ One study found a significant association between the duration of human milk consumption and lower BMI at 4 to 14 years of age in the full-sample analysis that was nonsignificant and in the opposite direction in the within-family analysis.^6^ One study assessed percent body fat, and found a significant association between consuming human milk for <2 months, compared with 5-7 months, and higher percent body fat at 62 years of age; however, there was not a full-sample analysis with which to compare the within-family analysis.

In summary, evidence for an association between the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity was inconsistent. One trend in the evidence emerged, which may help explain some of the inconsistencies in the findings between the studies. The direction of the statistically significant associations between the duration of human milk consumption and overweight and/or obesity differed somewhat between studies conducted in the United States and studies conducted in Europe. Four of the 5 studies reporting significant inverse associations between duration and overweight/obesity were from the United States,^6,12,28,42^ and all 3 studies reporting significant positive associations were from Europe.^24,25,29,30^ It is possible that the association between the duration of any human milk consumption and overweight and/or obesity differs between the United States and other populations (see Generalizability, below).

##### Precision

Nine of the 19 studies in this body of evidence had sufficient statistical power to detect significant associations. Of the 10 remaining studies, only 2 had wide confidence intervals suggestive of suboptimal statistical power.^34,38^ The remaining studies with nonsignificant findings were likely to have sufficient statistical power; in several cases they examined the duration of any human milk consumption as a continuous variable using a sizeable analytic sample (N=231 to 7417), and in other cases (i.e., when using categorical variables for duration of human milk consumption) the lack of significance was not attributable to a wide confidence interval but rather to the fact that the point estimates were close to the null.^4,10,13,18,23,26,33^

##### Directness

Most of the articles reported study objectives that included the examination of human milk consumption and overweight and/or obesity.

##### Generalizability

Seven of the 19 studies were conducted in the United States.^6,10,12,15,18,28,42^ The rest were from European countries, and there are some concerns about the generalizability of this evidence to U.S. populations, which may have higher risk of overweight and obesity than the populations from which participants were sampled in the European studies. For example, the authors of the cluster randomized trial in Belarus noted the much lower prevalence of obesity (i.e., about 5% of the sample at 16 years of age) in comparison to youth in the United States.^24,25^

Another limitation to the generalizability of the evidence is that the majority of evidence examined outcomes in childhood. Only 6 studies examined outcomes in adolescents,^6,10,12,18,24,30^ and only 1 study examined outcomes in adults.^34^

##### Risk of bias

Infant-feeding decisions can be strongly socially patterned, and in this largely observational body of evidence, 5 studies used approaches that were likely to reduce bias from confounding. First, there was 1 cluster randomized trial, and randomization mitigates confounding.^24,25^ Next, there were 4 observational studies that conducted within-family analyses of siblings fed differently in infancy.^6,10,12,34^ Such analyses reduce confounding from genetic and environmental factors, which siblings share; however, these studies had other risks of bias. For example, in 2 studies, mothers were asked to recall infant-feeding data when participants were between 10 and 18 years of age.^10,12^ In addition, in 2 studies, all participants reported their own height and weight,^12,34^ in a 3^rd^ study, some participants reported their own height and weight,^6^ and in the 4^th^ study, the method of anthropometric data collection was not reported.^10^

None of the remaining 14 studies controlled for all of the key confounders identified on the analytic framework, and the studies had other risks of bias, which varied between studies (Tables 7 and 8).

##### Publication bias

In addition to the graded elements of the assessment of the evidence, above, it is important to give consideration to publication bias. There is not a strong indication of publication bias because there are several published studies and they present evidence of associations that are both significant and nonsignificant, and inconsistent in direction.

##### Conclusion

Given this synthesis and assessment of the evidence, we conclude that insufficient evidence is available to determine the relationship between the duration of any human milk consumption among infants fed human milk and overweight and obesity at 2 years of age and older, because the available evidence is inconsistent.

Table 6 Evidence examining the relationship between the duration of any human milk consumption, among infants fed human milk, and overweight and/or obesity at 2 years of age and older^a^

Article; Study design (Study name); Country | Duration of any human milk exposure^b^ | Outcome^c^ | Significant findings | Nonsignificant findings
Outcomes from 2 to 5 years
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | OB* (β ± SE) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | Note: this analysis is across 3 age groups
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | In the full sample (N=8,237) | −0.007 ± 0.002; p<0.01
| | In the subsample of siblings (N=7,319) | −0.006 ± 0.002; p <0.05
| | In the subsample of siblings with discordant exposures (N=1,773) | | 0.001 ± 0.004; NS
Durmus 2011 ^9^; PC (Generation R); Netherlands | BF 0-3 mo vs BF >6 mo (ref) | OWOB§ (OR [95% CI]) | ~2 [~1.5, ~3]; p<0.01
Durmus 2011 ^9^; PC (Generation R); Netherlands | BF 0-3 mo vs BF >6 mo (ref) | @ 2 y (Total analytic N=5074) | ~2 [~1.5, ~3]; p<0.01
| | @ 3 y (Total analytic N=5074) | | ~0.9 [~0.8, ~2]
| BF 3-6 mo vs BF >6 mo (ref) | OWOB§ (OR [95% CI]) | ~2 [~1, ~3]; p<0.05
| BF 3-6 mo vs BF >6 mo (ref) | @ 2 y (Total analytic N=5074) | ~2 [~1, ~3]; p<0.05
| | @ 3 y (Total analytic N=5074) | | ~0.8 [~0.7, ~2]
Gubbels 2011 ^13^; PC (KOALA); Netherlands | BF duration (mo) | OWOB§ (OR [95% CI]) | | 1.01 [0.97,1.05]
Gubbels 2011 ^13^; PC (KOALA); Netherlands | BF duration (mo) | @2 y (N=1592) | | 1.01 [0.97,1.05]
| | @ 4 y (N=1733) | | 1.00 [0.96, 1.05]
Jiang 2013 ^18^; RC (CDS); U.S. | BF duration (mo) | OB* (effect ± SE) @ 5-18 y (N=1512) | | NS; data NR
Jiang 2013 ^18^; RC (CDS); U.S. | BF duration (mo) | Note: this analysis is across 3 age groups | | NS; data NR
Makela 2014 ^23^; PC (STEPS); Finland | Duration of any BF (mo) | OW § (OR) @ 2 y (N=848) | | 0.96; p=0.157
| | OB § (OR) @ 2 y (N=848) | | 0.93; p=0.141
Modrek 2017 ^28^; RC (Oregon PRAMS); U.S. | BF duration (wk) | OW ‡ @ 2 y instrumental variable estimate [weighted SE clustered at the county level] (N=447) | | −0.008 [−0.024, 0.004]; p<0.1
| | OB ‡ @ 2 y instrumental variable estimate [weighted SE clustered at the county level] (N=441) | −0.0082 [−0.018, −0.001]; p<0.05
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | BF <1 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR)
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | BF <1 mo vs BF ≥6 mo (ref) | @ 4 y
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | BF <1 mo vs BF ≥6 mo (ref) | in ALSPAC cohort (N=6522) | | ~1.0; NS
| | in EuroPrevall cohort (N=309) | | ~0.6; NS
| | in Generation XXI cohort (N=3387) | | ~0.9; NS
| | @ 5 y in EDEN cohort (N=1070) | | ~0.8; NS
| BF 1-3 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR)
| BF 1-3 mo vs BF ≥6 mo (ref) | @ 4 y
| BF 1-3 mo vs BF ≥6 mo (ref) | in ALSPAC cohort (N=6522) | | ~0.9; NS
| | in EuroPrevall cohort (N=309) | | ~0.7; NS
| | in Generation XXI cohort (N=3387) | | ~1.0; NS
| | @ 5 y in EDEN cohort (N=1070) | | ~0.8; NS
| BF 3-6 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR)
| BF 3-6 mo vs BF ≥6 mo (ref) | @ 4 y
| BF 3-6 mo vs BF ≥6 mo (ref) | in ALSPAC cohort (N=6522) | ~0.7; p=0.008
| | in EuroPrevall cohort (N=309) | | ~1.3; NS
| | in Generation XXI cohort (N=3387) | | ~1.1; NS
| | @ 5 y in EDEN cohort (N=1070) | | ~0.6; NS
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | BF 1-16 wk vs BF >16 wk (ref) | OWOB‡ (OR [95% CI]) in childhood (3-8 y); (Total analytic N=3963) | | 1.25 [0.98, 1.59]
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | BF 1-16 wk vs BF >16 wk (ref) | Note: this analysis is across 2 age groups | | 1.25 [0.98, 1.59]
| | OB‡ (OR [95% CI]) in childhood (3-8 y); (Total analytic N=3963) | 1.81 [1.07, 3.04]
| | Note: this analysis is across 2 age groups | 1.81 [1.07, 3.04]
Wojcicki 2015 ^42^; RC (Alaska PRAMS); U.S. | BF duration (mo) | OB^d^ (OR [95% CI]) @ 3 y
Wojcicki 2015 ^42^; RC (Alaska PRAMS); U.S. | BF duration (mo) | In Alaska non-Native children (N=474) | 0.95 [0.91, 0.995]; p=0.03
| | In Alaska Native children (N=226) | | 0.99 [0.96, 1.02]; p=0.44
Outcomes from 6 to 11 years
Bjertnaes 2019 ^4^; PC; Norway | Duration of partial BF (mo) | OWOB‡ (OR [95% CI] @ ~ 8 y; (N~181 OWOB, 770 Not OWOB) | | 1.02 [0.99, 1.06]; p=0.25
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | OB* (β ± SE) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | Note: this analysis is across 3 age groups
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | In the full sample (N=8,237) | −0.007 ± 0.002; p<0.01
| | In the subsample of siblings (N=7,319) | −0.006 ± 0.002; p <0.05
| | In the subsample of siblings with discordant exposures (N=1,773) | | 0.001 ± 0.004; NS
Durmus 2014 ^8^; PC (Generation R); Netherlands | BF duration trend (categories >0-1.9, 2-3.9, 4-5.9, ≥6 mo) | OWOB ‡ (OR [95% CI]) @ 6 y (N=5063) | p=0.02
| BF >0-1.9 mo vs BF ≥6 mo (ref) | OWOB‡ (OR [95% CI]) @ 6 y (N=1000, 1258) | ~0.7 [~0.6, ~1.0] (error bar just below 1.0)
| BF 2-3.9 mo vs BF ≥6 mo (ref) | OWOB‡ (OR [95% CI]) @ 6 y (N=836, 1258) | | ~0.8 [~0.7, ~1.1]
| BF 4-5.9 mo vs BF ≥6 mo (ref) | OWOB‡ (OR [95% CI]) @ 6 y (N=479, 1258) | | ~1.0 [~0.8, ~1.3]
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | OWOB* (OR ± SE from logit) @ 10-18 y
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | Note: this analysis is across 2 age groups
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | In the full sample (N=7417) | | 0.98 ± 0.00; p<0.10
| | In the subsample of siblings (N=1607) | | 0.98 ± 0.01; p<0.10
| | In the subsample of siblings with discordant exposures (N=470) | | 1.01 ± 0.01; NS
| | OB* (OR ± SE from logit) @ 10-18 y
| | Note: this analysis is across 2 age groups
| | In the full sample (N=7417) | | 0.98 ± 0.01; p<0.10
| | In the subsample of siblings (N=1607) | | 0.99 ± 0.01; NS
| | In the subsample of siblings with discordant exposures (N=470) | | 1.00 ± 0.02; NS
Gillman 2006 ^12^; CS (GUTS); U.S. | BF duration (per 3.7 mo, which was the mean difference in BF duration for discordant siblings) | OWOB* (OR [95% CI]) @ 9-14 y in the sample of siblings (N=5614) | 0.88 [0.82, 0.94]; (Adjusted for same confounders as discordant sibling analysis) | 0.94 [0.88, 1.00]; (Also adjusted for maternal BMI and smoking, household income)
Gillman 2006 ^12^; CS (GUTS); U.S. | BF duration (per 3.7 mo, which was the mean difference in BF duration for discordant siblings) | Note: this analysis is across 2 age groups | 0.88 [0.82, 0.94]; (Adjusted for same confounders as discordant sibling analysis) | 0.94 [0.88, 1.00]; (Also adjusted for maternal BMI and smoking, household income)
| BF longer than the mean BF duration of his/her participating sibship vs shorter | OWOB* (OR [95% CI]) @ 9-14 y in the subsample of siblings with discordant exposures (N=2372) | | 0.92 [0.76, 1.11]
| BF longer than the mean BF duration of his/her participating sibship vs shorter | Note: this analysis is across 2 age groups | | 0.92 [0.76, 1.11]
Heerman 2019 ^15^; PC (GROW); U.S. | BF any to 5 mo vs BF ≥6 mo (ref) | OB* (OR [95% CI]) @ ~7 y; (N= 128 ≤5/No OB, 60 ≤5/OB, 167 ≥6/No OB, 98 ≥6/OB) | . | 0.72 [0.46, 1.14]
Jiang 2013 ^18^; RC (CDS); U.S. | BF duration (mo) | OB* (effect ± SE) @ 5-18 y (N=1512) | | NS; data NR
Jiang 2013 ^18^; RC (CDS); U.S. | BF duration (mo) | Note: this analysis is across 3 age groups | | NS; data NR
Martin 2013 ^25^; RCT^e^ (PROBIT); Belarus | Intervention (higher rates of any BF measured @ 3, 6, 9, and 12 mo) vs Control | OWOB* (OR [95% CI]) @ 11.5 y | 1.18 [1.01, 1.39]
| | OB* (OR [95% CI]) @ 11.5 y | | 1.17 [0.97, 1.41]
Massion 2016 ^26^; PC (MCS); U.K. | Any BF <4 mo vs Any BF >4 mo (ref) | OWOB ‡ (RR [95% CI]) @ 11 y; (N=11,764) | | ~1.1 [~0.9, ~1.2]
Morgen 2018 ^29^; PC (DNBC); Denmark | BF 20.0-31.9 wk vs BF ≥40 wk (ref) | OWOB‡ (OR [95% CI])
Morgen 2018 ^29^; PC (DNBC); Denmark | BF 20.0-31.9 wk vs BF ≥40 wk (ref) | @ 7 y (Total analytic N=14,504) | 0.77 [0.64, 0.93]; p=0.006
| | @ 11 y (Total analytic N=8571) | 0.58 [0.43, 0.78]; p<0.0001
| BF 32.0-39.9 wk vs BF ≥40 wk (ref) | OWOB‡ (OR [95% CI]) | | 0.86 [0.73, 1.01]; p=0.7
| BF 32.0-39.9 wk vs BF ≥40 wk (ref) | @ 7 y (Total analytic N=14,504) | | 0.86 [0.73, 1.01]; p=0.7
| | @ 11 y (Total analytic N=8571) | | 0.82 [0.64, 1.04]; p=0.1
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | BF <1 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 9 y in ALSPAC cohort (N=7540) | | ~1.1; NS
| BF 1-3 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 9 y in ALSPAC cohort (N=7540) | | ~1.1; NS
| BF 3-6 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 9 y in ALSPAC cohort (N=7540) | | ~1.1; NS
Ortega-Garcia 2018 ^33^; PC (MALAMA); Spain | Duration of any BF (wk) | OWOB† (β [95% CI]) @ 6 y (N=231) | | 0.015 [−0.003, 0.032]; p=0.11
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | BF 1-16 wk vs BF >16 wk (ref) | OWOB‡ (OR [95% CI]) in childhood (3-8 y); (Total analytic N=3963) | | 1.25 [0.98, 1.59]
Ruijsbroek 2011 ^37^; PC (PIAMA); Netherlands | BF 1-16 wk vs BF >16 wk (ref) | Note: this analysis is across 2 age groups | | 1.25 [0.98, 1.59]
| | OB‡ (OR [95% CI]) in childhood (3-8 y); (Total analytic N=3963) | 1.81 [1.07, 3.04]
| | Note: this analysis is across 2 age groups | 1.81 [1.07, 3.04]
Skledar 2015 ^38^; RC; Croatia | BF duration (mo) | OWOB* (OR [95% CI]) @ 6-7 y (N=302) | | 1.45 [0.95, 2.20]; p=0.080
Outcomes from 12 to 19 years
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | OB* (β ± SE) @ 4-14 y
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | Note: this analysis is across 3 age groups
Colen 2014 ^6^; PC (Children of NLSY79); U.S. | BF duration (wk) | In the full sample (N=8,237) | −0.007 ± 0.002; p<0.01
| | In the subsample of siblings (N=7,319) | −0.006 ± 0.002; p <0.05
| | In the subsample of siblings with discordant exposures (N=1,773) | | 0.001 ± 0.004; NS
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | OWOB* (OR ± SE from logit) @ 10-18 y
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | Note: this analysis is across 2 age groups
Evenhouse 2005 ^10^; CS (Add Health); U.S. | Duration (mo) (quasi-continuous using midpoint of ranges 0-3, 3-6, 6-9, 9-12, 12-24, >24 mo) | In the full sample (N=7417) | | 0.98 ± 0.00; p<0.10
| | In the subsample of siblings (N=1607) | | 0.98 ± 0.01; p<0.10
| | In the subsample of siblings with discordant exposures (N=470) | | 1.01 ± 0.01; NS
| | OB* (OR ± SE from logit) @ 10-18 y
| | Note: this analysis is across 2 age groups
| | In the full sample (N=7417) | | 0.98 ± 0.01; p<0.10
| | In the subsample of siblings (N=1607) | | 0.99 ± 0.01; NS
| | In the subsample of siblings with discordant exposures (N=470) | | 1.00 ± 0.02; NS
Gillman 2006 ^12^; CS (GUTS); U.S. | BF duration (per 3.7 mo, which was the mean difference in BF duration for discordant siblings) | OWOB* (OR [95% CI]) @ 9-14 y in the sample of siblings (N=5614) | 0.88 [0.82, 0.94]; (Adjusted for same confounders as discordant sibling analysis) | 0.94 [0.88, 1.00]; (Also adjusted for maternal BMI and smoking, household income)
Gillman 2006 ^12^; CS (GUTS); U.S. | BF duration (per 3.7 mo, which was the mean difference in BF duration for discordant siblings) | Note: this analysis is across 2 age groups | 0.88 [0.82, 0.94]; (Adjusted for same confounders as discordant sibling analysis) | 0.94 [0.88, 1.00]; (Also adjusted for maternal BMI and smoking, household income)
| BF longer than the mean BF duration of his/her participating sibship vs shorter | OWOB* (OR [95% CI]) @ 9-14 y in the subsample of siblings with discordant exposures (N=2372) | | 0.92 [0.76, 1.11]
| BF longer than the mean BF duration of his/her participating sibship vs shorter | Note: this analysis is across 2 age groups | | 0.92 [0.76, 1.11]
Jiang 2013 ^18^; RC (CDS); U.S. | BF duration (mo) | OB* (effect ± SE) @ 5-18 y (N=1512) | | NS; data NR
Jiang 2013 ^18^; RC (CDS); U.S. | BF duration (mo) | Note: this analysis is across 3 age groups | | NS; data NR
Martin 2017 ^24^; RCT^e^ (PROBIT); Belarus | Intervention (higher rates of any BF measured @ 3, 6, 9, and 12 mo) vs Control | OWOB* (OR [95% CI]) @ 16 y (N=7064, 6493) | 1.14 [1.02-1.28]; p=0.03
| | OB* (OR [95% CI]) @ 16 y (N=7064, 6493) | | 1.09 [0.92-1.29]; p=0.31
Moschonis 2017 ^30^; RC (ALSPAC, EDEN, EuroPrevall, Generation XXI); U.K., France, Greece, Portugal | BF <1 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 13 y in ALSPAC cohort (N=6124) | | ~1.3; NS
| BF 1-3 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 13 y in ALSPAC cohort (N=6124) | | ~1.0; NS
| BF 3-6 mo vs BF ≥6 mo (ref) | OWOB †‡ (OR) @ 13 y in ALSPAC cohort (N=6124) | ~0.8; p=0.031
Outcomes at 20 years and older
O’Tierney 2009 ^34^; PC (Helsinki Birth Cohort); Finland | Trend across the BF duration categories <2, 3-4, 5-7, ≥8 mo | OW (% BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=206, 168, 233, 224) | | 42.7 vs 42.9 vs 41.2 vs 50.0; p=0.08 (linear), 0.50 (quadratic)
| BF <2 mo vs BF 5-7 mo (ref) | OW (difference, % BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=206, 233) | | 1.6 [−7.7, 11.0]
| BF 3-4 mo vs BF 5-7 mo (ref) | OW (difference, % BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=168, 233) | | 1.9 [−8.0, 11.8]
| BF ≥8 mo vs BF 5-7 mo (ref) | OW (difference, % BMI 25-30 kg/m2) from self-reported height and weight at ~62 y in a sample of siblings with discordant exposures (N=224, 233) | | 8.8 [−0.3, 18.0]

a Abbreviations: ALSPAC – Avon Longitudinal Study of Parents and Children, Add Health – National Longitudinal Study of Adolescent Health, BF – breastfeeding/breastfed, CDS – Child Development Supplement of the Panel Study of Income Dynamics, CI – confidence interval, CS – cross sectional, DNBC – Danish National Birth Cohort, EDEN - Etude des Déterminants pré et post natals de la santé et du développement de l’Enfant, FF – formula feeding/formula fed, Generation R – Generation Rotterdam, GROW – Growing Right Onto Wellness, GUTS – Growing Up Today Study, KOALA - Child, Parents, and Health: Lifestyle and Genetic Constitution, MCS – Millennium Cohort Study, mo – months, NLSY79 – National Longitudinal Survey on Youth 1979 Cohort, NS – nonsignificant, OB – obesity, OR – odds ratio, OW – overweight, OWOB – overweight and obesity, PC – prospective cohort study, PIAMA – Prevention and Incidence of Asthma and Mite Allergy, PRAMS - Pregnancy Risk Assessment Monitoring System, PROBIT – Promotion of Breastfeeding Intervention Trial, RC – retrospective cohort study, RCT – randomized controlled trial, ref – reference, SE – standard error, STEPS – Steps to Healthy Development, U.K. – United Kingdom, U.S. – United States of America, wk – weeks, y – years

b Exposures, from the articles included in the body of evidence, which address the duration of any human milk consumption among infants fed human milk

c Notations used for growth references: *CDC, †WHO, ‡IOTF, §Country-specific

d This study did not report the growth reference used

e RCT of an intervention to promote prolonged duration and exclusivity of breastfeeding rather than an RCT of breastfeeding, per se

Table 7 Risk of bias for the randomized controlled trial examining the relationship between the duration of any human milk consumption among infants fed human milk and overweight and obesity^a^,^b^

| Randomzation | Identification of participants - randomization | Deviations from intended interventions | Outcome measurement | Missing outcome data | Selection of the reported results
Martin 2013^25^ | Low | Some concerns | Low | Some concerns | Low | Low
Martin 2017^24^ | Low | Some concerns | Low | Some concerns | Low | Low

a A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

b Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 8 Risk of bias for observational studies examining the relationship between the duration of any human milk consumption among infants fed human milk and overweight and obesity^a^,^b^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Outcome measurement | Missing data | Selection of the reported results
Bjertnaes 2019^4^ | Serious | Serious | Serious | Low | Serious | Low | Low
Colen 2014^6^ | Serious | Serious | Serious | Low | Serious | Low | Low
Durmus 2014^8^ | Serious | Serious | Moderate | Low | Moderate | Moderate | Low
Durmus 2011^9^ | Serious | Moderate | Moderate | Low | Serious | Moderate | Low
Evenhouse 2005^10^ | Serious | Serious | Serious | Low | Serious | No information | Low
Gillman 2006^12^ | Serious | Serious | Serious | Low | Serious | Low | Low
Gubbels 2011^13^ | Serious | Serious | Moderate | Low | Serious | Serious | Low
Heerman 2019^15^ | Serious | Low | Moderate | Moderate | Moderate | Low | Low
Jiang 2013^18^ | Serious | Serious | Serious | Low | Serious | Low | Low
Makela 2014^23^ | Serious | Serious | Moderate | Low | Moderate | No information | Low
Massion 2016^26^ | Serious | Moderate | Moderate | Low | Serious | Serious | Low
Modrek 2017^28^ | Serious | Moderate | Moderate | Low | Serious | Moderate | Low
Morgen 2018^29^ | Serious | Serious | Moderate | Low | Serious | Serious | Low
Moschonis 2017^30^ | Serious | No information | Moderate | Low | Serious | No information | Low
O’Tierney 2009^34^ | Serious | Serious | Low | Low | Serious | Low | Low
Ortega-Garcia 2018^33^ | Serious | Low | Moderate | Low | Moderate | Serious | Low
Ruijsbroek 2011^37^ | Serious | Low | Moderate | Low | Serious | Moderate | Low
Skledar, 2015^38^ | Serious | Serious | Serious | Low | Moderate | Low | Low
Wojcicki, 2015^42^ | Serious | Moderate | Serious | Low | Serious | Serious | Low

a A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

b Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Duration of exclusive human milk consumption before the introduction of infant formula

Two articles, published in 2015 and 2018, were identified that met the inclusion criteria and examined the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and overweight and/or obesity at 2 years of age and older.^33,38^

Ortega-Garcia et al^33^ presented evidence from the Medio Ambiente y Lactancia Materna (MALAMA) study in Spain. Participants were born full term (i.e., gestational age >37 weeks) with a birthweight >2500g, had 1- and 5-minute Apgar scores of ≥7 and ≥8, respectively, and had infant-feeding and anthropometric data for the analyses (N=231). Infant-feeding data were reported prospectively by parents during interviews with trained nurses at birth and at 1, 3, 6, and 12 months of infant age. The study examined the number of weeks infants consumed human milk exclusively, before bottle feeding was introduced, as a continuous variable. Weight and height at 6 years of age were measured by pediatricians during well-child primary care visits, and the authors assessed overweight/obesity (i.e., BMI >1 SD based on WHO growth curves) at 6 years of age.

- The authors found a significant inverse association between the number of weeks participants consumed human milk and overweight/obesity at 6 years of age (β=−0.052 [95% CI −0.10, −0.003], p=0.04).

Skledar and Milosevic^38^ conducted a retrospective cohort study of Caucasian children who were in their first year of primary school in Croatia between 2002 and 2006. All children in the cohort were born full term (i.e., 37 to 42 weeks gestational age), and had complete data on infant feeding, anthropometry, and the confounding variables used in the analyses (N=302). Infant-feeding data, height, and weight were recorded in medical charts prospectively by primary care providers and obtained retrospectively for the study from a medical chart review. The authors compared infants who consumed human milk without additional formula with infants who consumed human milk with infant formula added to the diet before 3 months of age, and examined the odds of overweight/obesity at 6 to 7 years of age (i.e., BMI ≥85^th^ percentile based on CDC growth curves).

- A shorter duration of exclusive human milk consumption prior to the introduction of infant formula (i.e., <3 months), compared with a longer duration (i.e., ≥3 months), was associated with significantly higher odds of overweight/obesity at 6 to 7 years of age (OR 3.35 [95% CI 1.31, 8.60], p=0.012).

The 2 studies presented evidence that was consistent in direction, showing that shorter durations of exclusive human milk consumption, prior to the introduction of infant formula, are associated with higher risk of overweight and obesity at 6 to 7 years of age. However, the evidence from these 2 observational studies is insufficient to determine the relationship between the duration of exclusive human milk consumption prior to the introduction of infant formula and overweight and/or obesity at 2 years of age and older.^v^

Table 9 Evidence examining the relationship between the duration of exclusive human milk consumption before to the introduction of infant formula and and overweight and/or obesity at 2 years of age and older^a^

Article; Study design (Study name); Country | Duration of exclusive human milk exposure^b^ | Outcome^c^ | Significant findings | Nonsignificant findings
Ortega-Garcia 2018 ^33^; PC (MALAMA); Spain | Duration of full BF before bottle feeding first introduced (wk) | OWOB (β [95% CI]) @ 6 y; (N=231) | −0.052 [−0.10, −0.003]; p=0.04
Skledar 2015 ^38^; RC; Croatia | Addition of formula <3 mo vs BF without additional formula (ref) | OWOB* (OR [95% CI]) @ 6-7 y; (Total analytic N=302) | 3.35 [1.31, 8.60]; p=0.012

a Abbreviations: BF – breastfeeding/breastfed, CI – confidence interval, MALAMA – Medio Ambiente y Lactancia Materna, mo – months, OR – odds ratio, OWOB – overweight and obesity, PC – prospective cohort study, RC – retrospective cohort study, ref – reference, wk – week(s), y – year(s)

b Exposures, from the articles included in the body of evidence, which address the duration of exclusive human milk consumption prior to the introduction of infant formula

c Notations used for growth references: *CDC, †WHO, ‡IOTF, §Country-specific

Table 10 Risk of bias for observational studies examining the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and overweight and obesity^a^,^b^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Outcome measurement | Missing data | Selection of the reported results
Ortega-Garcia 2018^33^ | Serious | Low | Moderate | Low | Moderate | Serious | Low
Skledar, 2015^38^ | Serious | Serious | Serious | Low | Moderate | Low | Low

a A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

b Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Intensity, proportion, or amount of human milk consumed by mixed-fed infants

No articles were identified that examined the relationship between the intensity, proportion, or amount of human milk consumed by mixed-fed infants and overweight and/or obesity at 2 years of age and older.

### Intensity, proportion, or amount of human milk consumed at the breast versus by bottle

No articles were identified that examined the relationship between the intensity, proportion, or amount of human milk consumed at the breast versus by bottle and overweight and/or obesity at 2 years of age and older.

### Consuming human milk or infant formula (i.e., a single substance) during as single feeding session versus human milk and infant formula (e.g., “topping up”)

No articles were identified that examined the relationship between consuming human milk or infant formula (i.e., a single substance) during as single feeding session versus human milk and infant formula (e.g., “topping up”) and overweight and/or obesity at 2 years of age and older.

### Research recommendations

Conduct studies that are designed to reduce bias from confounding factors as much as possible. Sibling-pair studies are one example of this type of study design, but there are few such studies and they tend to have much smaller sample sizes than other types of observational studies. There is a need for larger sibling-pair studies, and for such studies to examine siblings that differ in terms of the duration of human milk consumption (e.g., <6 mo, ≥6 mo), not just with respect to ever vs. never consuming human milk.

Another way to approach these questions is with randomized trials of breastfeeding promotion, as was done in the PROBIT trial in Belarus^vi^. If the trial achieves substantial differences in duration or exclusivity of breastfeeding between intervention groups, this provides an opportunity to examine effects on subsequent overweight or obesity (and many other outcomes).

Observational studies that make use of large datasets, especially those that follow participants longitudinally and in particular, link children with siblings and parents, would also be very useful for more robustly assessing associations and providing more confidence in conclusions regarding causality. This could be achieved by linking surveillance systems that collect data about infant feeding and health outcomes (including overweight and obesity), and making use of emerging electronic medical record data. In general, observational studies need to pay careful attention to minimizing confounding, taking into account all of the key confounders in the analytical framework for this review including aspects of the child’s diet (complementary feeding and later dietary patterns). The use of instrumental variables such as Mendelian randomization approaches can also be helpful in minimizing confounding.

In both observational and intervention studies, researchers should consider effect modification in their study design whenever possible (e.g., child sex, parental obesity, socioeconomic status, child diets, child activity levels) to examine the impact of infant feeding on these outcomes within key subgroups.

### Included articles

1 Abraham EC, Godwin J, Sherriff A, Armstrong J. Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year. Public Health Nutr. 2012;15(9):1705–1714.doi: 10.1017/s1368980012002686.22626031
2 Anderson J, Hayes D, Chock L. Characteristics of overweight and obesity at age two and the association with breastfeeding in Hawai’i Women, Infants, and Children (WIC) participants. Matern Child Health J. 2014;18(10):2323–2331.doi: 10.1007/s10995-013-1392-9.24170508
3 Anderson PM, Butcher KF, Levine PB. Maternal employment and overweight children. J Health Econ. 2003;22(3):477–504.doi: 10.1016/s0167-6296(03)00022-5.12683963
4 Bjertnaes AA, Grundt JH, Donkor HM, . No significant associations between breastfeeding practices and overweight in 8-year-old children. Acta Paediatr. 2020;109(1):109–114.doi: 10.1111/apa.14937.31299109
5 Bohr AD, Boardman JD, Domingue BW, McQueen MB. Breastfeeding is associated with waist-to-height ratio in young adults. BMC Public Health. 2015;15:1281.doi: 10.1186/s12889-015-2611-7.26700003
6 Colen CG, Ramey DM. Is breast truly best? Estimating the effects of breastfeeding on long-term child health and wellbeing in the United States using sibling comparisons. Soc Sci Med. 2014;109:55–65.doi: 10.1016/j.socscimed.2014.01.027.24698713
7 de Jong C, Boehm G, Kikkert HK, Hadders-Algra M. The Groningen LCPUFA study: No effect of short-term postnatal long-chain polyunsaturated fatty acids in healthy term infants on cardiovascular and anthropometric development at 9 years. Pediatr Res. 2011;70(4):411–416.doi: 10.1203/PDR.0b013e31822a5ee0.21705958
8 Durmus B, Heppe DH, Gishti O, . General and abdominal fat outcomes in school-age children associated with infant breastfeeding patterns. Am J Clin Nutr. 2014;99(6):1351–1358.doi: 10.3945/ajcn.113.075937.24622802
9 Durmus B, van Rossem L, Duijts L, . Breast-feeding and growth in children until the age of 3 years: the Generation R Study. Br J Nutr. 2011;105(11):1704–1711.doi: 10.1017/s0007114510005374.21276279
10 Evenhouse E, Reilly S. Improved estimates of the benefits of breastfeeding using sibling comparisons to reduce selection bias. Health Serv Res. 2005;40(6 Pt 1):1781–1802.doi: 10.1111/j.1475-6773.2005.00453.x.16336548
11 Feldman-Winter L, Burnham L, Grossman X, Matlak S, Chen N, Merewood A. Weight gain in the first week of life predicts overweight at 2 years: A prospective cohort study. Matern Child Nutr. 2018;14(1).doi: 10.1111/mcn.12472.
12 Gillman MW, Rifas-Shiman SL, Berkey CS, . Breast-feeding and overweight in adolescence: within-family analysis [corrected]. Epidemiology. 2006;17(1):112–114.doi: 10.1097/01.ede.0000181629.59452.95.16357604
13 Gubbels JS, Thijs C, Stafleu A, van Buuren S, Kremers SP. Association of breast-feeding and feeding on demand with child weight status up to 4 years. Int J Pediatr Obes. 2011;6(2–2):e515–522.doi: 10.3109/17477166.2010.514343.20858157
14 Hawkins SS, Baum CF, Rifas-Shiman SL, Oken E, Taveras EM. Examining Associations between Perinatal and Postnatal Risk Factors for Childhood Obesity Using Sibling Comparisons. Child Obes. 2019;15(4):254–261.doi: 10.1089/chi.2018.0335.30883194
15 Heerman WJ, Sommer EC, Slaughter JC, Samuels LR, Martin NC, Barkin SL. Predicting Early Emergence of Childhood Obesity in Underserved Preschoolers. J Pediatr. 2019;213:115–120.doi: 10.1016/j.jpeds.2019.06.031.31353040
16 Heppe DH, Kiefte-de Jong JC, Durmus B, . Parental, fetal, and infant risk factors for preschool overweight: the Generation R Study. Pediatr Res. 2013;73(1):120–127.doi: 10.1038/pr.2012.145.23138398
17 Huang DY, Lanza HI, Anglin MD. Trajectory of Adolescent Obesity: Exploring the Impact of Prenatal to Childhood Experiences. J Child Fam Stud. 2014;23(6):1090–1101.doi: 10.1007/s10826-013-9766-6.25332643
18 Jiang M, Foster EM. Duration of breastfeeding and childhood obesity: a generalized propensity score approach. Health Serv Res. 2013;48(2 Pt 1):628–651.doi: 10.1111/j.1475-6773.2012.01456.x.22924637
19 Layte R, Bennett A, McCrory C, Kearney J. Social class variation in the predictors of rapid growth in infancy and obesity at age 3 years. Int J Obes (Lond). 2014;38(1):82–90.doi: 10.1038/ijo.2013.160.23979218
20 Lee JW, Lee M, Lee J, Kim YJ, Ha E, Kim HS. The Protective Effect of Exclusive Breastfeeding on Overweight/Obesity in Children with High Birth Weight. J Korean Med Sci. 2019;34(10):e85.doi: 10.3346/jkms.2019.34.e85.30886551
21 Li N, Strobino D, Ahmed S, Minkovitz CS. Is there a healthy foreign born effect for childhood obesity in the United States? Matern Child Health J. 2011;15(3):310–323.doi: 10.1007/s10995-010-0588-5.20229329
22 Lurbe E, Aguilar F, Alvarez J, Redon P, Torro MI, Redon J. Determinants of Cardiometabolic Risk Factors in the First Decade of Life: A Longitudinal Study Starting at Birth. Hypertension. 2018;71(3):437–443.doi: 10.1161/hypertensionaha.117.10529.29358459
23 Makela J, Vaarno J, Kaljonen A, Niinikoski H, Lagstrom H. Maternal overweight impacts infant feeding patterns--the STEPS Study. Eur J Clin Nutr. 2014;68(1):43–49.doi: 10.1038/ejcn.2013.229.24219892
24 Martin RM, Kramer MS, Patel R, . Effects of Promoting Long-term, Exclusive Breastfeeding on Adolescent Adiposity, Blood Pressure, and Growth Trajectories: A Secondary Analysis of a Randomized Clinical Trial. JAMA Pediatr. 2017;171(7):e170698.doi: 10.1001/jamapediatrics.2017.0698.28459932
25 Martin RM, Patel R, Kramer MS, . Effects of promoting longer-term and exclusive breastfeeding on adiposity and insulin-like growth factor-I at age 11.5 years: a randomized trial. Jama. 2013;309(10):1005–1013.doi: 10.1001/jama.2013.167.23483175
26 Massion S, Wickham S, Pearce A, Barr B, Law C, Taylor-Robinson D. Exploring the impact of early life factors on inequalities in risk of overweight in UK children: findings from the UK Millennium Cohort Study. Arch Dis Child. 2016;101(8):724–730.doi: 10.1136/archdischild-2015-309465.27162002
27 Metzger MW, McDade TW. Breastfeeding as obesity prevention in the United States: a sibling difference model. Am J Hum Biol. 2010;22(3):291–296.doi: 10.1002/ajhb.20982.19693959
28 Modrek S, Basu S, Harding M, . Does breastfeeding duration decrease child obesity? An instrumental variables analysis. Pediatr Obes. 2017;12(4):304–311.doi: 10.1111/ijpo.12143.27161761
29 Morgen CS, Angquist L, Baker JL, Andersen AN, Sorensen TIA, Michaelsen KF. Breastfeeding and complementary feeding in relation to body mass index and overweight at ages 7 and 11 y: a path analysis within the Danish National Birth Cohort. Am J Clin Nutr. 2018;107(3):313–322.doi: 10.1093/ajcn/nqx058.29566190
30 Moschonis G, de Lauzon-Guillain B, Jones L, . The effect of early feeding practices on growth indices and obesity at preschool children from four European countries and UK schoolchildren and adolescents. Eur J Pediatr. 2017;176(9):1181–1192.doi: 10.1007/s00431-017-2961-5.28711955
31 Moss BG, Yeaton WH. Early childhood healthy and obese weight status: potentially protective benefits of breastfeeding and delaying solid foods. Matern Child Health J. 2014;18(5):1224–1232.doi: 10.1007/s10995-013-1357-z.24057991
32 Nelson MC, Gordon-Larsen P, Adair LS. Are adolescents who were breast-fed less likely to be overweight? Analyses of sibling pairs to reduce confounding. Epidemiology. 2005;16(2):247–253.doi: 10.1097/01.ede.0000152900.81355.00.15703541
33 Ortega-Garcia JA, Kloosterman N, Alvarez L, . Full Breastfeeding and Obesity in Children: A Prospective Study from Birth to 6 Years. Child Obes. 2018;14(5):327–337.doi: 10.1089/chi.2017.0335.29912590
34 O’Tierney PF, Barker DJ, Osmond C, Kajantie E, Eriksson JG. Duration of breast-feeding and adiposity in adult life. J Nutr. 2009;139(2):422s–425s.doi: 10.3945/jn.108.097089.19106318
35 Pattison KL, Kraschnewski JL, Lehman E, . Breastfeeding initiation and duration and child health outcomes in the first baby study. Prev Med. 2019;118:1–6.doi: 10.1016/j.ypmed.2018.09.020.30287329
36 Pluymen LPM, Wijga AH, Gehring U, Koppelman GH, Smit HA, van Rossem L. Breastfeeding and cardiometabolic markers at age 12: a population-based birth cohort study. Int J Obes (Lond). 2019;43(8):1568–1577.doi: 10.1038/s41366-018-0317-5.30886238
37 Ruijsbroek A, Wijga AH, Kerkhof M, Koppelman GH, Smit HA, Droomers M. The development of socio-economic health differences in childhood: results of the Dutch longitudinal PIAMA birth cohort. BMC Public Health. 2011;11:225.doi: 10.1186/1471-2458-11-225.21486447
38 Skledar MT, Milosevic M. Breastfeeding and time of complementary food introduction as predictors of obesity in children. Cent Eur J Public Health. 2015;23(1):26–31.doi: 10.21101/cejph.a3956.26036095
39 Thorland W, Currie D, Colangelo C. Status of High Body Weight Among Nurse-Family Partnership Children. MCN Am J Matern Child Nurs. 2017;42(6):352–357.doi: 10.1097/nmc.0000000000000369.29049059
40 van Rossem L, Taveras EM, Gillman MW, . Is the association of breastfeeding with child obesity explained by infant weight change? Int J Pediatr Obes. 2011;6(2–2):e415–422.doi: 10.3109/17477166.2010.524700.20979572
41 Weng SF, Redsell SA, Nathan D, Swift JA, Yang M, Glazebrook C. Estimating overweight risk in childhood from predictors during infancy. Pediatrics. 2013;132(2):e414–421.doi: 10.1542/peds.2012-3858.23858427
42 Wojcicki JM, Young MB, Perham-Hester KA, de Schweinitz P, Gessner BD. Risk factors for obesity at age 3 in Alaskan children, including the role of beverage consumption: results from Alaska PRAMS 2005-2006 and its three-year follow-up survey, CUBS, 2008-2009. PLoS One. 2015;10(3):e0118711.doi: 10.1371/journal.pone.0118711.25793411

ii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii U.S. National Library of Medicine. Clinicaltrials.gov. Version 10 October 2013. Internet: https://clinicaltrials.gov/ct2/show/NCT01561612#wrapper

iv A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

v A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

vi Kramer, M. S., Chalmers, B., Hodnett, E. D., Sevkovskaya, Z., Dzikovich, I., Shapiro, S., … & Shishko, G. (2001). Promotion of Breastfeeding Intervention Trial (PROBIT): a randomized trial in the Republic of Belarus. JAMA, 285(4), 413–420.11242425