# List of abbreviations

Abbreviation: Full name
25(OH)D: 25-hydroxy vitamin D
AA: Arachidonic acid
ALA: Alpha-linolenic acid
CNPP: Center for Nutrition Policy and Promotion
DHA: Docosahexaenoic acid
FDA: U.S. Food and Drug Administration
FNS: USDA Food and Nutrition Service
HHS: U.S. Department of Health and Human Services
HLA: Human leukocyte antigen
LA: Linoleic acid
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
ONGA: Office of Nutrition Guidance and Analysis
USDA: U.S. Department of Agriculture