# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^xiii^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 4. Duration, Frequency, and Volume of Exclusive Human Milk and/or Infant Formula Feeding.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that will be examined and evaluated, including the target population, exposures, comparisons, outcomes, and key confounders. This is the analytic framework for the systematic review on the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and nutrient status. For this systematic review, the exposures examined were the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and the comparators examined were different durations, frequencies, and volumes. These exposures and comparators were examined in infants and toddlers from birth to 24 months who are full-term, and healthy or at risk for chronic disease. The outcomes examined were iron status, iron deficiency and anemia, zinc status, iodine status, vitamin D status, vitamin B12 status, and fatty acid status. These outcomes were examined in infants and toddlers from birth to 24 months. The key confounding variables considered were sex (for iron status outcome), race/ethnicity, socioeconomic status, types/amounts of complementary foods and beverages, vitamin/mineral supplements, birth weight/fetal growth/gestational age, and Maternal anthropometry. Other factors to be considered were timing of cord clamping (for iron status outcomes), maternal prenatal vitamin/mineral supplement, and inflammatory biomarkers (for iron, zinc, and vitamin D status outcomes).

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics that were used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 21 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Publication status | Articles that have been peer-reviewed | Articles that have not been peer-reviewed and are not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, and conference proceedings
Date of publication | January 1980-September 2019 | Articles published prior to January 1980 or after September 2019
Language of publication | Articles published in English | Articles published in languages other than English
Study design | Randomized controlled trials; Non-randomized controlled trials, including quasi-experimental and controlled before-and-after studies; Prospective cohort studies; Retrospective cohort studies; Nested case-control studies | Uncontrolled trials; Case-control studies; Cross-sectional studies; Uncontrolled before-and-after studies; Narrative reviews; Systematic reviews; Meta-analyses
Interventions/exposures | 1 Duration of exclusive human milk and/or infant formula consumption:; a) Ever consuming human milk (i.e., any amount of human milk feeding)
Interventions/exposures | - b) Duration of any human milk consumption among infants fed human milk; c) Duration of exclusive human milk consumption prior to the introduction of infant formula | 1b) Variables that include infants who were never fed human milk; 1c) Duration of exclusive human milk consumption prior to the introduction of complementary foods and beverages or the concurrent introduction of complementary foods and beverages and infant formula (including when a study does not specify what follows exclusive human milk feeding)
Interventions/exposures | 2 Frequency and volume of human milk and/or infant formula consumption
Interventions/exposures | - a) Intensity/proportion/amount of human milk consumed by mixed-fed infants | 2a) Variables that include infants fed complementary foods and beverages
Comparators | 1 Different durations of exclusive human milk and/or infant formula consumption:
Comparators | - a) Never consuming human milk | 1a) Variables that include any amount of human milk feeding (e.g., very short-term or token) or the feeding of infant formula that does not meet the definition below
Comparators | - b) Different durations of any human milk consumption among infants fed human milk | 1b) Variables that include infants who were never fed human milk
Comparators | - c) Different durations of exclusive human milk consumption prior to the introduction of infant formula | 1c) Durations of exclusive human milk consumption prior to the introduction of complementary foods and beverages or the concurrent introduction of complementary foods and beverages and infant formula (including when a study does not specify what follows exclusive human milk feeding)
Comparators | 2 Different frequencies and volumes of human milk and/or infant formula consumption
Comparators | - a) Different intensities/proportions/amounts of human milk consumed by mixed-fed infants | 2a) Variables that include infants fed complementary foods and beverages
Sources of foods, beverages, or nutrients | Human milk: Mother’s own milk (MOM), that is, human milk fed at the breast (i.e., nursing) or expressed and fed fresh or after refrigeration/freezing | Human milk from third parties (e.g., banked/donor milk)
Sources of foods, beverages, or nutrients | Infant formula: commercially prepared infant formula meeting FDA^xiv^ and/or Codex Alimentarius^xv^ international food standards | Infant formulas that are not commercially prepared or that do not meet FDA and/or Codex Alimentarius international food standards
Outcomes | - Iron status (e.g., hemoglobin concentration, hematocrit, serum ferritin concentration, serum transferrin receptor); - Iron deficiency and anemia; - Zinc status (e.g., plasma zinc concentration); - Iodine status; - Vitamin D status; - Vitamin B12 status; - Fatty acid status
Country | Studies conducted in countries ranked as high or very high human development^xvi^ | Studies conducted in countries ranked as medium or lower human development
Study participants | Human participants; Males; Females | Non-human participants (e.g., animal and in-vitro studies)
Age of study participants | Age at intervention or exposure: infants and toddlers (birth to 24 months) | Children and adolescents (ages 2 years and older)
Age of study participants | Age at outcome: infants and toddlers (birth to 24 months) | Adults (ages 19 years and older)
Health status of study participants | Studies that enroll participants:; - born full-term (≥37 weeks and 0/7 days gestational age); - who are healthy and/or at risk for chronic disease; Studies that enroll some participants:; - born preterm (gestational age <37 weeks and 0/7 days), with low birth weight (<2500g), or small for gestational age; - diagnosed with a disease; - who are deficient in the nutrients of interest or have anemia | Studies that exclusively enroll participants:; - born preterm (gestational age <37 weeks and 0/7 days), with low birth weight (<2500g), or small for gestational age; - diagnosed with a disease or hospitalized with an illness or injury; - who are deficient in the nutrients of interest or have anemia (i.e., studies that aim to treat participants who have already been diagnosed with nutrient deficiencies or anemia)
Size of study groups | Studies with ≥30 participants per study group or a power analysis indicating that the study is appropriately powered for the outcome(s) of interest | Studies with <30 participants per study group with no power analysis indicating that the study is appropriately powered for the outcome(s) of interest

### Electronic databases and search terms

#### Pregnancy and Birth to 24 Months Project literature search^xvii^

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: Dec 4, 2015 and March 28, 2016 to refine/limit search terms and remove pub type indexing
- Date range searched: January 1, 1980-March 28, 2016
- Search terms:
  - (breast feeding[mh] OR breastfeeding[tiab] OR breast feeding*[tiab] OR breast-feeding*[tiab] OR breastfed[tiab] OR breast-fed[tiab] OR breastfeed*[tiab] OR “breast feed”[tiab]) OR (Milk, human[mh] OR “breast milk”[tiab] OR breast-milk[tiab] OR “human milk”[tiab] OR “mother’s milk”[tiab] OR breastmilk[tiab]) OR (Bottle feeding[mh] OR bottle feeding*[tiab] OR “bottle feeding”[tiab] OR bottle-feeding*[tiab] OR bottle-fed[tiab] OR “bottle fed”[tiab])
  - NOT ((aids[ti] AND “Acquired Immunodeficiency Syndrome”[Mesh]) OR hiv[ti] OR HIV/AIDS[ti] OR human immunodefic*[ti] OR Acquired Immunodefic*[ti] OR “low birth weight”[ti] OR lbw[ti] OR vlbw[ti] OR elbw[ti] OR pcb[ti] OR pcbs[ti] OR Polychlorinated Biphenyl*[ti] OR Polychlorobiphenyl Compound*[ti] OR dioxin*[ti] OR (breast[ti] AND (tumor*[ti] OR tumour*[ti] OR cancer*[ti] OR carcinoma*[ti] OR disease*[ti]))) NOT (breastfeed*[ti] OR breastfed*[ti] OR feed*[ti] OR fed[ti] OR milk[ti])
  - NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic[sb])
    Filters: Publication date from 1980/01/01 to 2016/03/28, Humans, English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) searched: Dec 8, 2015
- Date range searched: January 1, 1980-December 8, 2015
- Search terms:
  - “Breast Feeding” OR breast-fed OR “breast fed” OR breastfeeding OR “breast feeding” OR “breast feed” OR “breast feeds” OR breast-feed OR breast-feeds OR (breast NEAR/3 feed*) OR “human milk” OR “breast milk” OR breastmilk OR “mother’s milk” OR “maternal milk” OR ((mother* OR maternal OR donor* OR donate*) NEAR/3 milk) OR “Bottle feeding” OR “bottle feedings” OR “bottle-feeding” OR “bottle-feedings” OR (bottle NEAR/3 feed*)

##### Embase

- Provider: Elsevier
- Date(s) Searched: Dec 5, 2015
- Date range searched: January 1, 1980-December 5, 2015
- Search terms^xviii^:
  - ‘bottle feeding’/exp OR ‘bottle feeding‘:ab,ti OR ‘bottle feedings‘:ab,ti OR ‘bottle fed‘:ab,ti OR bottle* NEAR/3 feed* AND [english]/lim AND [humans]/lim AND [1980-2015]/py OR ‘breast milk’/exp OR ‘human milk‘:ab,ti OR ‘breast milk‘:ab,ti OR breastmilk:ab,ti OR mother* NEAR/2 milk OR ‘maternal milk‘:ab,ti AND [english]/lim AND [humans]/lim AND [1980-2015]/py OR ‘breast feeding’/exp OR breastfeed*:ab,ti OR ‘breast feed‘:ab,ti OR ‘breast feeding‘:ab,ti OR breastfed:ab,ti OR ‘breast fed‘:ab,ti OR feeding NEAR/3 breast AND [english]/lim AND [humans]/lim AND [1980-2015]/py

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) searched: Dec 8, 2015
- Date range searched: January 1, 1980-December 8, 2015
- Search terms:
  - (MH “Breast Feeding+” OR breast-fed OR “breast fed” OR breastfeeding OR breast feeding OR breast-fed) OR MH “Milk, Human” OR “Human Milk” OR “Breast Milk” OR Breastmilk OR breast-milk OR ((maternal OR mother*) n3 milk) OR (MH “Bottle Feeding”) OR “bottle feeding” OR (bottle n3 feed*) OR bottle-feeding OR bottle-feedings OR “bottle fed” OR “bottle-fed”)

#### Update to the Pregnancy and Birth to 24 Months Project literature search

##### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: September 5, 2019
- Date range searched: January 1, 2016 - September 31, 2019
- Search terms:
  - #1 - Breast feeding[mh] OR breast fed[tiab] OR breast feed*[tiab] OR bottle feed*[tiab] OR breastfeed*[tiab] OR bottle fed*[tiab] OR breastfed[tiab] OR breastfeed*[tiab] OR breast feed[tiab] OR Milk, human[mh] OR “breast milk”[tiab] OR “human milk”[tiab] OR “mother’s milk”[tiab] OR mothers’ milk[tiab] OR mother’s own milk[tiab] OR mothers’ own milk[tiab] OR “maternal milk”[tiab] OR breastmilk[tiab] OR Bottle feeding[mh] OR infant formula[mh] OR “infant formula”[tiab] OR “milk formula”[tiab]
  - #2 - ((“Allergy and Immunology"[Mesh:NoExp] OR allergy[tiab] OR allergies[tiab] OR allergic[tiab] OR allergen* OR Hypersensitivit*[tiab] OR atopic[tiab]) AND (food OR foods OR peanut* OR nut OR nuts OR egg OR eggs OR milk OR shellfish OR fish OR wheat OR gluten* OR dairy)) OR “Food Hypersensitivity”[Mesh] OR asthma*[tiab] OR asthma[mh] OR “Rhinitis, Allergic”[Mesh] OR (allergic[tiab] AND rhiniti*[tiab]) OR “Dermatitis, Atopic”[Mesh] OR ((Dermatiti*[tiab] OR eczema[tiab]) AND Atopic[tiab]) OR eczema[mh] OR “Immunoglobulin E”[Mesh] OR “Immunoglobulin E”[tiab]
  - #3 - “Body Weights and Measures”[Mesh] OR “Body Weight”[Mesh] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR body mass index[tiab] OR BMI[tiab] OR underweight[tiab] OR wasting[tiab] OR healthy weight[tiab] OR “Body Composition”[Mesh] OR body composition[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR stunting[tiab] OR stunted[tiab] OR “Growth Charts”[Mesh] OR growth chart*[tiab] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR Anthropometry[Mesh:NoExp]OR Growth[Mesh:NoExp] OR Overnutrition[Mesh] OR failure to thrive[mh] OR anthropometr*[tiab] OR adiposity[tiab] OR calf circumference[tiab] OR failure to thrive[tiab] OR skin fold*[tiab] OR skin fold*[tiab] OR normal weight[tiab] OR weight for age[tiab] OR height for age[tiab] OR recumbent length[tiab] OR length for age[tiab] OR weight for length[tiab]
  - #4 - “Mental Disorders”[Mesh] OR mental disorder*[tiab] OR “Cognition”[Mesh] OR cognition[tiab] OR cognitive[tiab] OR metacognition[tiab] OR neurocognitive[tiab] OR neurodevelop*[tiab] OR neurological[tiab] OR “Cognitive Dysfunction”[Mesh] OR “Depressive Disorder”[Mesh] OR “Depression”[Mesh] OR depression[tiab] OR anxiety[tiab] OR “Psychomotor Performance”[Mesh] OR motor skill*[tiab] OR “Executive Function”[Mesh] OR executive function* OR “Attention Deficit and Disruptive Behavior Disorders”[Mesh] OR attention deficit disorder*[tiab] OR ADHD[tiab] OR “Child Behavior Disorders”[Mesh] OR developmental disorder*[tiab] OR “Autism Spectrum Disorder”[Mesh] OR Autism[tiab] OR Asperger[tiab] OR language processing[tiab] OR language delay* OR “Child Development”[Mesh] OR child develop*[tiab] OR “Developmental Disabilities”[Mesh] OR developmental delay[tiab] OR developmental disabilit*[tiab] OR “Motor Skills Disorders”[Mesh] OR motor skill*[tiab] OR “Problem Solving”[Mesh] OR developmental domain* OR academic performance[tiab] OR academic achievement[tiab] OR academic failure[tiab] OR academic success*[tiab]
  - #5 - Micronutrients[mh] OR micronutrient*[tiab] OR “Anemia”[Mesh] OR “Anemia, Iron-Deficiency”[Mesh] OR anemia[tiab] OR anemic[tiab] OR rickets[tiab] OR hematocrit[tiab] OR 25 hydroxyvitamin d[tiab] OR “25(oh)d”[tiab] OR cobalamin[tiab] OR holo-tc[tiab] OR holotranscobalamin[tiab] OR “Zinc”[Mesh] OR zinc[tiab] OR “Iodine”[Mesh] OR iodine[tiab] OR “Iron”[Mesh] OR iron[tiab] OR hemoglobin*[tiab] OR ferritin*[tiab] OR transferrin*[tiab] OR “Vitamin B 12”[Mesh] OR “Vitamin B 12 Deficiency”[Mesh] OR “vitamin B”[tiab] OR “Vitamin D”[Mesh] OR “Vitamin D Deficiency”[Mesh] OR vitamin D*[tiab] OR “Fatty Acids”[Mesh:NoExp] OR fatty acid* OR saturated fat* OR “Fatty Acids, Monounsaturated”[Mesh] OR monounsaturated fat* OR mono-unsaturated fat* OR polyunsaturated fat* OR poly-unsaturated fat* OR unsaturated fat* OR unsaturated fatty acid* OR “Fatty Acids, Omega-3”[Mesh] OR omega-3[tiab] OR N-3 fatty acid* OR “Fatty Acids, Omega-6"[Mesh] OR omega-6 OR N-6 fatty acid* OR MUFA* OR PUFA* OR alpha-linolenic acid* OR eicosapentaenoic acid* OR docosahexaenoic acid* OR linoleic acid* OR alpha-linolenic acid* OR arachidonic acid* OR “Fats, Unsaturated”[Mesh] OR (((fat[tiab] OR fatty[tiab]) AND (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR linolenic acid*)))))
  - #6 - Diabetes Mellitus[mh:noexp] OR Diabetes Mellitus, Type 2[Mesh] OR Type 2 diabetes[tiab] OR T2D[tiab] OR T1D[tiab] OR homa-ir[tiab] OR blood pressure[mh] OR hypertension[mh] OR hyperlipidemias[mh] OR hyperlipidemia*[tiab] OR thrombosis[mh] OR “blood pressure”[tiab] OR hdl[tiab] OR ldl[tiab] OR Diabetes Mellitus, Type 1[mesh] OR Type 1 diabetes[tiab] OR Prediabetic State[Mesh] OR prediabet*[tiab] OR pre diabet* OR Insulin Resistance[Mesh] OR insulin resistance[tiab] OR Glucose Intolerance[Mesh] OR glucose intolerance[tiab] OR glucose tolerance[tiab] OR Glycated Hemoglobin A[Mesh] OR hemoglobin A1c[ti] OR ((impaired fasting[tiab] OR Diabetes Mellitus[Mesh:NoExp]) AND (glucose[tiab] OR glycemi*[tiab] OR high blood sugar[tiab] OR low blood sugar[tiab] OR hyperglycemia[mh] OR hypoglycemia[mh] OR hyperglycem*[tiab] OR hypoglycem*[tiab])) OR ((Cardiovascular Diseases[Mesh:noexp] OR cardiovascular disease*[tiab] OR coronary artery disease[tiab] OR heart disease*[tiab] OR Heart Failure[Mesh] OR heart failure[tiab] OR myocardial infarction*[tiab] OR Myocardial Ischemia[Mesh] OR Myocardial Ischemia*[tiab] OR Stroke[Mesh] OR stroke[tiab] OR heart attack[tiab] OR venous thrombosis[tiab] OR hypertension[tiab] OR Lipids/blood[Mesh] OR total cholesterol[tiab] OR Triglycerides[Mesh] OR triglycerides[tiab] OR arterial occlusive diseases[mh]))
  - #7 - #2 OR #3 OR #4 OR #5 OR #6
  - #8 - #1 AND #7
  - #9 - #8 NOT (“Animals"[Mesh] NOT (“Animals"[Mesh] AND “Humans”[Mesh])) NOT editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]
    Filters: Publication date from 2016/01/01 to 2019/09/31; English

##### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: September 5, 2019
- Date range searched: January 1, 2016 - September 31, 2019
- Search terms:
  - #1 - [mh “breast feeding”] OR “breast fed” OR “breast feed*” OR “bottle feed*” OR breastfeed* OR “bottle fed*” OR breastfed OR breastfeed* OR “breast feed” OR [mh “milk, human”] OR “breast milk” OR “human milk” OR “mother’s milk” OR “mothers’ milk” OR “mother’s own milk” OR “mothers’ own milk” OR “maternal milk” OR breastmilk OR [mh “Bottle feeding”] OR [mh “infant formula”] OR “infant formula” OR “milk formula”
  - #2 - [mh ^"Allergy and Immunology"] OR ((allerg*:ti,ab OR Hypersensitivit*:ti,ab) NEAR/4 (food* OR peanut* OR nut OR nuts OR egg* OR milk OR shellfish OR wheat OR dairy OR fish)) OR [mh “Food Hypersensitivity”] OR asthma* OR [mh “Rhinitis, Allergic”] OR (allerg* NEAR/4 Rhiniti*) OR [mh “Dermatitis, Atopic”] OR ((Dermatiti* OR eczema) NEAR/4 Atopic) OR (Infant* NEAR/4 Eczema) OR [mh “Immunoglobulin E”] OR “Immunoglobulin E”
  - #3 – [mh “Body Weights and Measures”] OR [mh “Body Weight”) OR obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR [mh “Body Composition”] OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR stunting OR stunted OR [mh “Growth Charts”] OR growth chart* OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR [mh ^“Anthropometry”] OR [mh ^“Growth”] OR [mh “Overnutrition”] OR [mh “failure to thrive”] OR anthropometr* OR adiposity OR “calf circumference” OR “failure to thrive” OR “skin fold*” OR “skin fold*” OR “normal weight” OR “weight for age” OR “height for age” OR “recumbent length” OR “length for age” OR “weight for length”
  - #4 - [mh “Mental Disorders”] OR [mh “Cognition”] OR [mh “Cognitive Dysfunction”] OR [mh “Depressive Disorder”] OR [mh “Depression”] OR [mh “Psychomotor Performance”] OR [mh “Executive Function”] OR [mh “Attention Deficit and Disruptive Behavior Disorders”] OR [mh “Child Behavior Disorders”] OR [mh “Autism Spectrum Disorder”] OR [mh “Child Development”] OR [mh “Developmental Disabilities”] OR [mh “Motor Skills Disorders”] OR [mh “Problem Solving”] OR (“mental disorder*” OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR depression OR anxiety OR “motor skill*” OR “executive function*” OR “attention deficit disorder*” OR ADHD OR “developmental disorder*” OR Autism OR Asperger OR “language processing” OR “language delay” OR “child develop*” OR “developmental delay” OR “developmental disabilit*” OR “motor skill*” OR “developmental domain*” OR “academic performance” Or “academic achievement” OR “academic failure” OR “academic success*”):ti,ab,kw
  - #5 - [mh Micronutrients] OR micronutrient* OR [mh “Anemia”] OR [mh “Anemia, Iron-Deficiency”] OR anemia OR anemic OR rickets OR hematocrit OR “25 hydroxyvitamin d” OR “25(oh)d” OR cobalamin OR holo-tc OR holotranscobalamin OR [mh “Zinc”] OR zinc OR [mh “Iodine”] OR iodine OR [mh “Iron”] OR iron OR hemoglobin* OR ferritin* OR transferrin* OR [mh “Vitamin B 12”] OR [mh “Vitamin B 12 Deficiency”] OR “vitamin B” OR [mh “Vitamin D”] OR [mh “Vitamin D Deficiency”] OR “vitamin D*” OR [mh ^"Fatty Acids”] OR “fatty acid*” OR “saturated fat*” OR [mh “Fatty Acids, Monounsaturated”] OR “monounsaturated fat*” OR “mono-unsaturated fat*” OR “poly-unsaturated fat*” OR “polyunsaturated fat*” OR “unsaturated fat*” OR “unsaturated fatty acid*” OR [mh “Fatty Acids, Omega-3”] OR omega-3 OR “N-3 fatty acid*” OR [mh “Fatty Acids, Omega-6”] OR omega-6 OR “N-6 fatty acid*” OR MUFA* OR PUFA* OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linoleic acid*” OR “alpha-linolenic acid*” OR “arachidonic acid*” OR [mh “Fats, Unsaturated”] OR ((fat OR fatty) NEAR/4 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR linolenic acid*))
  - #6 - [mh ^”Diabetes Mellitus”] OR [mh “Diabetes Mellitus, Type 2”] OR “Type 2 diabetes” OR T2D OR T1D OR homa-ir OR [mh “blood pressure”] OR [mh “hypertension”] OR [mh “hyperlipidemias”] OR hyperlipidemia* OR [mh “thrombosis”] OR “blood pressure” OR hdl OR ldl OR [mh “Diabetes Mellitus, Type 1”] OR “Type 1 diabetes” OR [mh “Prediabetic State”] OR prediabet* OR “pre diabet*” OR [mh “Insulin Resistance”] OR “insulin resistance” OR [mh “Glucose Intolerance”] OR “glucose intolerance” OR “glucose tolerance” OR [mh “Glycated Hemoglobin A”] OR “hemoglobin A1c” OR ((“impaired fasting” OR [mh ^“Diabetes Mellitus”]) NEAR/4 (glucose OR glycemi* OR “high blood sugar” OR “low blood sugar” OR [mh hyperglycemia] OR [mh hypoglycemia] OR hyperglycem* OR hypoglycem*)) OR [mh “Cardiovascular Diseases”] OR “cardiovascular disease*” OR “coronary artery disease” OR “heart disease*” OR [mh “Heart Failure”] OR “heart failure” OR “myocardial infarct*” OR [mh “Myocardial Ischemia”] OR “Myocardial Ischemia*” OR [mh Stroke] OR stroke OR “heart attack” OR “venous thrombosis” OR hypertension OR [mh Lipids/BL] OR “total cholesterol” OR [mh Triglycerides] OR triglycerides OR [mh “arterial occlusive diseases”]
  - #6 - #2 OR #3 OR #4 OR #5 OR #6
  - #7 - #1 AND #6
    Filters – Date limited 2016 to 2019, Trials

##### Embase

- Provider: Elsevier
- Date(s) Searched: September 5, 2019
- Date range searched: January 1, 2016 - September 31, 2019
- Search terms:
  - #1 - breast AND ‘feeding’/exp OR ‘breast fed’:ti,ab OR ‘bottle feed*’:ti,ab OR ‘bottle fed*’:ti,ab OR breastfed:ti,ab OR breastfeed*:ti,ab OR ‘breast feed*’:ti,ab OR ‘breast milk’/exp OR ‘breast milk’:ti,ab OR ‘human milk’:ti,ab OR ‘mothers milk’:ti,ab OR ‘mothers own milk’:ti,ab OR ‘maternal milk’:ti,ab OR breastmilk:ti,ab OR ‘bottle feeding’/exp OR ‘artificial milk’/exp OR ‘infant formula’:ti,ab OR ‘milk formula’:ti,ab
  - #2 - ‘allergic asthma’/exp OR ‘food allergy’/exp OR ‘allergic rhinitis’/exp OR ‘dermatitis’/exp OR ‘eczema’/exp OR ‘skin allergy’/exp OR ((allerg* OR hypersensitivity*) NEAR/4 (food OR peanut* OR nut OR nuts OR egg OR eggs OR milk OR shellfish OR wheat OR fish OR dairy)) OR ‘immunoglobulin e’/exp OR ‘immunoglobulin e’:ti,ab
  - #3 - ‘morphometry’/exp OR obesity:ti,ab OR obese:ti,ab OR overweight:ti,ab OR ‘body mass index’:ti,ab OR bmi:ti,ab OR underweight:ti,ab OR wasting:ti,ab OR ‘healthy weight’:ti,ab OR ‘body composition’:ti,ab OR ‘body fat’:ti,ab OR ‘fat mass’:ti,ab OR ‘fat free mass’:ti,ab OR stunting:ti,ab OR stunted:ti,ab OR ‘growth chart*’:ti,ab OR ‘waist circumference’:ti,ab OR ‘head circumference’:ti,ab OR ‘arm circumference’:ti,ab OR ‘thigh circumference’:ti,ab OR ‘neck circumference’:ti,ab OR anthropometr*:ti,ab OR adiposity:ti,ab OR ‘calf circumference’:ti,ab OR ‘failure to thrive’:ti,ab OR ‘skin fold*’:ti,ab OR skinfold*:ti,ab OR ‘normal weight’:ti,ab OR ‘weight for age’:ti,ab OR ‘height for age’:ti,ab OR ‘recumbent length’:ti,ab OR ‘length for age’:ti,ab OR ‘weight for length’:ti,ab OR ‘body composition’/mj OR ‘waist circumference’/de OR ‘body height’/de OR ‘growth chart’/de OR ‘body weight’/de OR ‘anthropometry’/exp OR ‘body growth’/de OR ‘growth’/de OR ‘overnutrition’/de OR ‘failure to thrive’/exp OR ‘weight for age’/exp OR ‘height for age’/exp OR ‘length for age’/exp
  - #4 - ((micronutrient*:ti,ab OR anemia:ti,ab OR anemic:ti,ab OR rickets:ti,ab OR hematocrit:ti,ab OR ‘25 hydroxyvitamin d’:ti,ab OR ‘25(oh)d’:ti,ab OR cobalamin:ti,ab OR ‘holo tc’:ti,ab OR holotranscobalamin:ti,ab OR zinc:ti,ab OR iodine:ti,ab OR iron:ti,ab OR hemoglobin*:ti,ab OR ferritin*:ti,ab OR transferrin*:ti,ab OR ‘vitamin b’:ti,ab OR ‘vitamin d*’:ti,ab OR ‘fatty acid*’:ti,ab OR ‘saturated fat*’:ti,ab OR ‘monounsaturated fat*’:ti,ab OR mono-unsaturated) AND fat*:ti,ab OR ‘polyunsaturated fat*’:ti,ab OR poly-unsaturated) AND fat* OR ‘unsaturated fat*’:ti,ab OR ‘unsaturated fatty acid*’:ti,ab OR ‘omega 3’:ti,ab OR ‘n-3 fatty acid*’:ti,ab OR ‘omega 6’:ti,ab OR ‘n-6 fatty acid*’:ti,ab OR mufa*:ti,ab OR pufa*:ti,ab OR ‘eicosapentaenoic acid*’:ti,ab OR ‘docosahexaenoic acid*’:ti,ab OR ‘linoleic acid*’:ti,ab OR ‘alpha-linolenic acid*’:ti,ab OR ‘arachidonic acid*’:ti,ab OR ((fat:ti,ab OR fatty:ti,ab) AND (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR linolenic) AND acid*) OR ‘trace element’/exp OR ‘anemia’/exp OR ‘zinc’/exp OR ‘iodine’/exp OR ‘iron’/exp OR ‘cyanocobalamin’/exp OR ‘b12 deficiency’/exp OR ‘vitamin d’/exp OR ‘vitamin d deficiency’/exp OR ‘fatty acid’/de OR ‘docosahexaenoic acid’/exp OR ‘icosapentaenoic acid’/exp OR ‘linoleic acid’/exp OR ‘linolenic acid’/exp OR ‘arachidonic acid’/exp OR ‘holotranscobalamin’/exp OR ‘hemoglobin’/exp OR ‘ferritin’/exp OR ‘transferrin’/exp
  - #5 - ‘type 2 diabetes’:ti,ab OR t2d:ti,ab OR t1d:ti,ab OR ‘homa ir’:ti,ab OR hyperlipidemia*:ti,ab OR ‘blood pressure’:ti,ab OR hdl:ti,ab OR ldl:ti,ab OR ‘type 1 diabetes’:ti,ab OR prediabet*:ti,ab OR ‘pre diabet*’:ti,ab OR ‘insulin resistance’:ti,ab OR ‘glucose intolerance’:ti,ab OR ‘glucose tolerance’:ti,ab OR ‘hemoglobin a1c’:ti,ab OR ((‘impaired fasting’:ti,ab OR ‘diabetes mellitus’/de) AND (glucose:ti,ab OR glycemi*:ti,ab OR ‘high blood sugar’:ti,ab OR ‘low blood sugar’:ti,ab OR ‘hyperglycemia’/exp OR ‘hypoglycemia’/exp OR hyperglycem*:ti,ab OR hypoglycem*:ti,ab)) OR ‘cardiovascular disease*’:ti,ab OR ‘coronary artery disease’:ti,ab OR ‘heart disease*’:ti,ab OR ‘heart failure’:ti,ab OR ‘myocardial infarction*’:ti,ab OR ‘myocardial ischemia*’:ti,ab OR stroke:ti,ab OR ‘heart attack’:ti,ab OR ‘venous thrombosis’:ti,ab OR hypertension:ti,ab OR ‘total cholesterol’:ti,ab OR triglycerides:ti,ab OR ‘diabetes mellitus’/de OR ‘non insulin dependent diabetes mellitus’/exp OR ‘blood pressure’/exp OR ‘hypertension’/exp OR ‘hyperlipidemia’/exp OR ‘thrombosis’/exp OR ‘insulin dependent diabetes mellitus’/exp OR ‘impaired glucose tolerance’/exp OR ‘insulin resistance’/exp OR ‘glucose intolerance’/exp OR ‘glycosylated hemoglobin’/exp OR ‘cardiovascular disease’/de OR ‘heart failure’/exp OR ‘heart muscle ischemia’/exp OR ‘heart infarction’/exp OR ‘cerebrovascular accident’/exp OR ‘blood lipids’/exp OR ‘triacylglycerol’/exp OR ‘peripheral occlusive artery disease’/exp
  - #6 - ‘mental disease’/exp OR ‘cognition’/exp OR ‘cognitive defect’/exp OR ‘depression’/exp OR ‘psychomotor performance’/de OR ‘executive function’/de OR ‘attention deficit disorder’/de OR ‘autism’/exp OR ‘child development’/de OR ‘developmental disorder’/exp OR ‘psychomotor disorder’/de OR ‘problem solving’/de OR ‘mental disorder*’:ab,ti OR cognition:ab,ti OR cognitive:ab,ti OR metacognition:ab,ti OR neurocognitive:ab,ti OR neurodevelop*:ab,ti OR neurological:ab,ti OR depression:ab,ti OR anxiety:ab,ti OR ‘executive function*’:ab,ti OR ‘attention deficit disorder*’:ab,ti OR adhd:ab,ti OR ‘developmental disorder*’:ab,ti OR autism:ab,ti OR asperger:ab,ti OR ‘language processing’:ab,ti OR ‘language delay’:ab,ti OR ‘child develop*’:ab,ti OR ‘developmental delay’:ab,ti OR ‘developmental disabilit*’:ab,ti OR ‘motor skill*’:ab,ti OR ‘developmental domain*’:ab,ti OR ‘academic performance’:ab,ti OR ‘academic achievement’:ab,ti OR ‘academic failure’:ab,ti OR ‘academic success*’:ab,ti
  - #7 - #2 OR #3 OR #4 OR #5 OR #6
  - #8 - #1 AND #7
  - #9 - #8 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2016-2019]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

##### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: September 5, 2019
- Date range searched: January 1, 2016 - September 31, 2019
- Search terms:
  - #1 - [mh “breast feeding”] OR “breast fed” OR “breast feed*” OR “bottle feed*” OR breastfeed* OR “bottle fed*” OR breastfed OR breastfeed* OR “breast feed” OR [mh “milk, human”] OR “breast milk” OR “human milk” OR “mother’s milk” OR “mothers’ milk” OR “mother’s own milk” OR “mothers’ own milk” OR “maternal milk” OR breastmilk OR [mh “Bottle feeding”] OR [mh “infant formula”] OR “infant formula” OR “milk formula”
  - #2 - (mh “Allergy and Immunology”) OR ((allerg* OR Hypersensitivit*) N4 (food* OR peanut* OR nut OR nuts OR egg* OR milk OR shellfish OR wheat OR dairy OR fish)) OR (mh “Food Hypersensitivity+”) OR asthma* OR (mh “Rhinitis, Allergic”) OR (allerg* N4 Rhiniti*) OR (mh “Dermatitis, Atopic”) OR ((Dermatiti* OR eczema) N4 Atopic)) OR (Infant* N5 Eczema) OR (mh “Immunoglobulin E”) OR “Immunoglobulin E”
  - #3 - (mh “Body Weights and Measures”) OR (mh “Body Weight”) OR obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR (mh “Body Composition”) OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR stunting OR stunted OR (mh “Growth Charts”) OR growth chart* OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR (mh “Anthropometry”) OR (mh “Growth”) OR (mh “Overnutrition”) OR (mh “failure to thrive”) OR anthropometr* OR adiposity OR “calf circumference” OR “failure to thrive” OR “skin fold*” OR “skin fold*” OR “normal weight” OR “weight for age” OR “height for age” OR “recumbent length” OR “length for age” OR “weight for length”
  - #4 - (mh Micronutrients) OR micronutrient* OR (mh Anemia) OR (mh “Anemia, Iron-Deficiency”) OR anemia OR anemic OR rickets OR hematocrit OR “25 hydroxyvitamin d” OR “25(oh)d” OR cobalamin OR holo-tc OR holotranscobalamin OR (mh Zinc) OR zinc OR (mh Iodine) OR iodine OR (mh Iron) OR iron OR hemoglobin* OR ferritin* OR transferrin* OR (mh “Vitamin B 12”) OR (mh “Vitamin B 12 Deficiency”) OR “vitamin B” OR “vitamin b12” OR “vitamin b 12” OR (mh “Vitamin D”) OR “vitamin d” OR (mh “Vitamin D Deficiency”) OR “vitamin D*” OR (mh “Fatty Acids”) OR fatty acid* OR saturated fat* OR (mh “Fatty Acids, Monounsaturated”) OR monounsaturated fat* OR mono-unsaturated fat* OR polyunsaturated fat* OR poly-unsaturated fat* OR unsaturated fat* OR unsaturated fatty acid* OR (mh “Fatty Acids, Omega-3”) OR omega-3* OR N-3 fatty acid* OR (mh “Fatty Acids, Omega-6”) OR omega-6* OR N-6 fatty acid* OR MUFA* OR PUFA* OR “alpha-linolenic acid*” OR “eicosapentaenoic acid*” OR “docosahexaenoic acid*” OR “linoleic acid*” OR “alpha-linolenic acid*” OR “arachidonic acid*” OR (mh “Fats, Unsaturated”) OR (((fat OR fatty) N4 (saturat* OR unsatur* OR monounsatur* OR polyunsatur* OR poly-unsatur* OR linolenic acid*)))))
  - #5 - (mh “Diabetes Mellitus”) OR (mh “Diabetes Mellitus, Type 2”) OR “Type 2 diabetes” OR T2D OR T1D OR homa-ir OR (mh “blood pressure”) OR (mh hypertension) OR (mh hyperlipidemias) OR hyperlipidemia* OR (mh thrombosis) OR “blood pressure” OR hdl OR ldl OR (mh “Diabetes Mellitus, Type 1”) OR “Type 1 diabetes” OR (mh “Prediabetic State”) OR prediabet* OR “pre diabet*” OR (mh “Insulin Resistance”) OR “insulin resistance” OR (mh “Glucose Intolerance”) OR “glucose intolerance” OR “glucose tolerance” OR (mh “Glycated Hemoglobin A”) OR “hemoglobin A1c” OR ((“impaired fasting” OR (mh “Diabetes Mellitus”)) N4 (glucose OR glycemi* OR “high blood sugar” OR “low blood sugar” OR (mh hyperglycemia) OR (mh hypoglycemia) OR hyperglycem* OR hypoglycem*)) OR (mh “Cardiovascular Diseases”) OR cardiovascular disease* OR coronary artery disease* OR heart disease* OR (mh “Heart Failure”) OR “heart failure” OR “myocardial infarction” OR (mh “Myocardial Ischemia”) OR “Myocardial Ischemia” OR (mh Stroke) OR stroke OR “heart attack” OR “venous thrombosis” OR hypertens* OR (mh “Lipids/BL”) OR “total cholesterol” OR (mh Triglycerides) OR triglycerides OR (mh “arterial occlusive diseases”)
  - #6 - (MH “Mental Disorders+”) OR “mental disorder*” OR (MH “Cognition+”) OR cognition OR cognitive OR metacognition OR neurocognitive OR neurodevelop* OR neurological OR “cognitive dysfunction” OR “depressive disorders OR (MH “Depression”) OR depression OR (MH “Anxiety”) OR anxiety OR (MH “Psychomotor Performance”) OR motor skill* OR (MH “Executive Function”) OR executive function* OR (MH “Attention Deficit Hyperactivity Disorder”) OR attention deficit disorder* OR ADHD OR (MH “Child Behavior Disorders”) OR developmental disorder* OR (MH “Autistic Disorder”) OR autism OR Asperger OR “language processing” OR language delay* OR (MH “Child Development”) OR child develop* OR (MH “Developmental Disabilities”) OR developmental delay* OR developmental disabilit* OR (MH “Motor Skills Disorders”) OR motor skill* OR (MH “Problem Solving”) OR developmental domain* OR “academic performance” OR “academic achievement” OR “academic failure” OR academic success*
  - #7 - #2 OR #3 OR #4 OR #5 OR #6
  - #8 - #1 AND #7
  - #9 - #8 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication)
    Filters: Published Date: 2016 to 2019, English Language; Human

## LITERATURE SEARCH AND SCREENING RESULTS

Figure 2 Pregnancy and Birth to 24 Months Project literature search^xix^

The flow chart below illustrates the search and screening results for the first literature search. The results of the electronic database searches, after the removal of duplicates^xx^, were screened independently by 2 NESR analysts using a step-wise process by reviewing titles and abstracts together, followed by full-texts, to determine which articles met the inclusion criteria. Refer to Table 22 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases. Manually identified articles were also screened to determine whether they met criteria for inclusion.

The literature search in PubMed, Embase, Cochrane, and CINAHL retrieved 31,335 records after the removal of duplicates. Title and abstract screening resulted in the exclusion of 28,358 articles, and full-text screening of the remaining 2,977 records resulted in the exclusion of 2,956 articles for this question. No additional articles were identified via manual search of the references of included articles and existing systematic reviews. Therefore, 21 articles were included in the systematic reveiw from this literature search.

Figure 3 Update to the Pregnancy and Birth to 24 Months Project literature search

The flow chart below illustrates the search and screening results for the second literature search. The results of the electronic database searches, after removal of duplicates, were screened independently by 2 NESR analysts using a step-wise process by reviewing titles, followed by abstracts, followed by full-texts, to determine which articles met the inclusion criteria. Refer to Table 23 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases. Manually identified articles were also screened to determine whether they met criteria for inclusion.

The literature search in PubMed, Embase, Cochrane, and CINAHL retrieved 12,106 records, which was reduced to 7,290 records after the removal of duplicates. Title screening resulted in the exclusion of 5,178 articles, abstract screening resulted in the exclusion of 1,483 articles, and full-text screening resulted in the exclusion of 627 articles for this question. No additional articles were identified via manual search of the references of included articles and existing systematic reviews. Therefore, 2 articles were included in the systematic reveiw from this literature search.

### Excluded articles

Table 22 Full-text exclusions, Pregnancy and Birth to 24 Months Project literature search^xxi^

The table below lists the articles excluded after full-text screening of the Pregnancy and Birth to 24 Months Project literature search. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

| Full texts screened | Reason for exclusion
1 | Aarts, C.,Kylberg, E.,Hofvander, Y.,Gebre-Medhin, M. (2003). Growth under privileged conditions of healthy Swedish infants exclusively breastfed from birth to 4-6 months: a longitudinal prospective study based on daily records of feeding Acta Paediatr, 92(2), 145-51 | Size of study groups, Intervention/exposure
2 | Abarin, T.,Yan Wu, Y.,Warrington, N.,Lye, S.,Pennell, C.,Briollais, L. (2012). The impact of breastfeeding on FTO-related BMI growth trajectories: an application to the Raine pregnancy cohort study Int J Epidemiol, 41(6), 1650-60 | Intervention/exposure
3 | Abdel-Hafeez, E. H.,Belal, U. S.,Abdellatif, M. Z. M.,Naoi, K.,Norose, K. (2013). Breast-feeding protects infantile diarrhea caused by intestinal protozoan infections Korean Journal of Parasitology, 51(5), 519-524 | Participant health
4 | Abdoll, G. S. (2001). Report on the nursing bottle caries campaign launched by the Free State Oral Health Services Sadj, 56(1), 32-3 | Study design
5 | Abdulmoneim, I.,Al-Ghamdi, S. A. (2001). Relationship between breast-feeding duration and acute respiratory infections in infants Saudi Med J, 22(4), 347-50 | Study design, Participant health
6 | Abdul-Razzak, K. K.,Ajlony, M. J.,Khoursheed, A. M.,Obeidat, B. A. (2011). Vitamin D deficiency among healthy infants and toddlers: a prospective study from Irbid, Jordan Pediatr Int, 53(6), 839-45 | Study design, Intervention/exposure
7 | Aberg, N.,Engstrom, I.,Lindberg, U. (1989). Allergic diseases in Swedish school children Acta Paediatr Scand, 78(2), 246-52 | Study design
8 | Abraham, E. C.,Godwin, J.,Sherriff, A.,Armstrong, J. (2012). Infant feeding in relation to eating patterns in the second year of life and weight status in the fourth year Public Health Nutr, 15(9), 1705-14 | Outcome
9 | Abuekteish, F.,Alwash, R.,Hassan, M.,Daoud, A. S. (1996). Prevalence of asthma and wheeze in primary school children in northern Jordan Ann Trop Paediatr, 16(3), 227-31 | Study design
10 | Abusaad, Fawzia E.,El-Gilany, Abdel-Hady (2011). Exclusive breastfeeding and infant morbidity in Sakaka City, Saudi Arabia Middle East Journal of Nursing, 5(6), 3-8 6p | Intervention/exposure, Outcome
11 | Adgent, M. A.,Hoffman, K.,Goldman, B. D.,Sjodin, A.,Daniels, J. L. (2014). Brominated flame retardants in breast milk and behavioural and cognitive development at 36 months Paediatr Perinat Epidemiol, 28(1), 48-57 | Intervention/exposure
12 | Adlakha, A. L.,Suchindran, C. M. (1985). Factors affecting infant and child mortality J Biosoc Sci, 17(4), 481-96 | Study design
13 | Agache, I.,Ciobanu, C. (2010). Risk factors and asthma phenotypes in children and adults with seasonal allergic rhinitis Phys Sportsmed, 38(4), 81-6 | Study design, Size of study groups
14 | Agarwal, D. K.,Agarwal, K. N.,Khare, B. B. (1985). Study on current status of infant and childhood feeding practices Indian Pediatr, 22(9), 716 | Country, Study design
15 | Agostoni, C. (2001). Breast-feeding, human milk, long-chain polyunsaturated fatty acids and development Dev Med Child Neurol Suppl, 86(#issue#), 8-9 | Study design
16 | Agostoni, C.,Fiocchi, A.,Riva, E.,Terracciano, L.,Sarratud, T.,Martelli, A.,Lodi, F.,D’Auria, E.,Zuccotti, G.,Giovannini, M. (2007). Growth of infants with IgE-mediated cow’s milk allergy fed different formulas in the complementary feeding period Pediatr Allergy Immunol, 18(7), 599-606 | Participant health, Intervention/exposure
17 | Agostoni, C.,Grandi, F.,Gianni, M. L.,Silano, M.,Torcoletti, M.,Giovannini, M.,Riva, E. (1999). Growth patterns of breast fed and formula fed infants in the first 12 months of life: an Italian study Arch Dis Child, 81(5), 395-9 | Outcome
18 | Agostoni, C.,Grandi, F.,Scaglioni, S.,Gianni, M. L.,Torcoletti, M.,Radaelli, G.,Fiocchi, A.,Riva, E. (2000). Growth pattern of breastfed and nonbreastfed infants with atopic dermatitis in the first year of life Pediatrics, 106(5), E73 | Intervention/exposure
19 | Agostoni, C.,Marangoni, F.,Giovannini, M.,Galli, C.,Riva, E. (2001). Prolonged breast-feeding (six months or more) and milk fat content at six months are associated with higher developmental scores at one year of age within a breast-fed population Adv Exp Med Biol, 501(#issue#), 137-41 | Size of study groups
20 | Agostoni, C.,Marangoni, F.,Lammardo, A. M.,Giovannini, M.,Riva, E.,Galli, C. (2001). Breastfeeding duration, milk fat composition and developmental indices at 1 year of life among breastfed infants Prostaglandins Leukot Essent Fatty Acids, 64(2), 105-9 | Outcome
21 | Agostoni, C.,Riva, E.,Bellu, R.,Trojan, S.,Luotti, D.,Giovannini, M. (1994). Effects of diet on the lipid and fatty acid status of full-term infants at 4 months J Am Coll Nutr, 13(6), 658-64 | Size of study groups
22 | Agostoni, C.,Trojan, S.,Bellu, R.,Riva, E.,Giovannini, M. (1995). Neurodevelopmental quotient of healthy term infants at 4 months and feeding practice: the role of long-chain polyunsaturated fatty acids Pediatr Res, 38(2), 262-6 | Outcome
23 | Agras, W. S.,Kraemer, H. C.,Berkowitz, R. I.,Hammer, L. D. (1990). Influence of early feeding style on adiposity at 6 years of age J Pediatr, 116(5), 805-9 | Size of study groups
24 | Agras, W. S.,Kraemer, H. C.,Berkowitz, R. I.,Korner, A. F.,Hammer, L. D. (1987). Does a vigorous feeding style influence early development of adiposity? J Pediatr, 110(5), 799-804 | Intervention/exposure
25 | Agre, F. (1985). The relationship of mode of infant feeding and location of care to frequency of infection Am J Dis Child, 139(8), 809-11 | Intervention/exposure
26 | Ahn, C. H.,MacLean, W. C., Jr. (1980). Growth of the exclusively breast-fed infant Am J Clin Nutr, 33(2), 183-92 | Study design, Intervention/exposure
27 | Ahn, S. K.,Kam, S.,Chun, B. Y. (2014). Incidence of and factors for self-reported fragility fractures among middle-aged and elderly women in rural Korea: An 11-year follow-up study Journal of Preventive Medicine and Public Health, 47(6), 289-297 | Participant age
28 | Ajetunmobi, O. M.,Whyte, B.,Chalmers, J.,Tappin, D. M.,Wolfson, L.,Fleming, M.,MacDonald, A.,Wood, R.,Stockton, D. L. (2015). Breastfeeding is associated with reduced childhood hospitalization: evidence from a Scottish Birth Cohort (1997-2009) J Pediatr, 166(3), 620-5 e4 | Intervention/exposure
29 | Ajrouche, R.,Rudant, J.,Orsi, L.,Petit, A.,Baruchel, A.,Lambilliotte, A.,Gambart, M.,Michel, G.,Bertrand, Y.,Ducassou, S.,Gandemer, V.,Paillard, C.,Saumet, L.,Blin, N.,Hemon, D.,Clavel, J. (2015). Childhood acute lymphoblastic leukaemia and indicators of early immune stimulation: the Estelle study (SFCE) Br J Cancer, 112(6), 1017-26 | Outcome
30 | Akeson, P. K.,Axelsson, I. E.,Raiha, N. C.,Warm, A.,Minoli, I.,Moro, G. (2000). Fat intake and metabolism in Swedish and Italian infants Acta Paediatr, 89(1), 28-33 | Intervention/exposure
31 | Akeson, P. M.,Axelsson, I. E.,Raiha, N. C. (1998). Growth and nutrient intake in three- to twelve-month-old infants fed human milk or formulas with varying protein concentrations J Pediatr Gastroenterol Nutr, 26(1), 1-8 | Study design, Intervention/exposure, Size of study groups
32 | Akeson, P. M.,Axelsson, I. E.,Raiha, N. C. (1999). Plasma lipids and apolipoproteins in breastfed and formula-fed Swedish infants Acta Paediatr, 88(1), 1-6 | Outcome
33 | Akkus, Z.,Camdeviren, H.,Celik, F.,Gur, A.,Nas, K. (2005). Determination of osteoporosis risk factors using a mutiple logistic regression model in postmenopausal Turkish women Saudi Medical Journal, 26(9), 1351-1359 | Participant age
34 | Al Mamun, A.,O’Callaghan, M. J.,Williams, G. M.,Najman, J. M.,Callaway, L.,McIntyre, H. D. (2015). Breastfeeding is protective to diabetes risk in young adults: a longitudinal study Acta Diabetol, 52(5), 837-44 | Outcome
35 | Al-Abbad, A. A.,Bella, H. (1990). Diarrhoea in the under-fives in a Saudi semiurban community Tropical and Geographical Medicine, 42(3), 233-237 | Study design
36 | al-Ali, F. M.,Hossain, M. M.,Pugh, R. N. (1997). The associations between feeding modes and diarrhoea among urban children in a newly developed country Public Health, 111(4), 239-43 | Intervention/exposure
37 | Alaluusua, S.,Lukinmaa, P. L.,Koskimies, M.,Pirinen, S.,Holtta, P.,Kallio, M.,Holttinen, T.,Salmenpera, L. (1996). Developmental dental defects associated with long breast feeding Eur J Oral Sci, 104(5-6), 493-7 | Size of study groups
38 | Alaluusua, S.,Myllarniemi, S.,Kallio, M.,Salmenpera, L.,Tainio, V. M. (1990). Prevalence of caries and salivary levels of mutans streptococci in 5-year-old children in relation to duration of breast feeding Scand J Dent Res, 98(3), 193-6 | Outcome
39 | Alam, S.,Ahmad, S. A.,Kumar, S. (2001). Dietary regimen for persistent diarrhea in infants under four months Indian Pediatr, 38(4), 396-400 | Country
40 | Al-Atawi, M. S.,Al-Alwan, I. A.,Al-Mutair, A. N.,Tamim, H. M.,Al-Jurayyan, N. A. (2009). Epidemiology of nutritional rickets in children Saudi J Kidney Dis Transpl, 20(2), 260-5 | Study design
41 | Alati, R.,Van Dooren, K.,Najman, J. M.,Williams, G. M.,Clavarino, A. (2009). Early weaning and alcohol disorders in offspring: biological effect, mediating factors or residual confounding? Addiction, 104(8), 1324-32 | Outcome
42 | Albert, R. J.,Cantin, R. Y.,Cross, H. G.,Castaldi, C. R. (1988). Nursing caries in the Inuit children of the Keewatin J Can Dent Assoc, 54(10), 751-8 | Study design
43 | al-Dashti, A. A.,Williams, S. A.,Curzon, M. E. (1995). Breast feeding, bottle feeding and dental caries in Kuwait, a country with low-fluoride levels in the water supply Community Dent Health, 12(1), 42-7 | Study design
44 | Alderete, T. L.,Autran, C.,Brekke, B. E.,Knight, R.,Bode, L.,Goran, M. I.,Fields, D. A. (2015). Associations between human milk oligosaccharides and infant body composition in the first 6 mo of life Am J Clin Nutr, 102(6), 1381-8 | Intervention/exposure
45 | Alexander, D. A. (2003). Breastfeeding study needs to be viewed in context…‘Breastfeeding may increase the risk of asthma and allergies’ (Specialty News Bulletin, December 2002) RN, 66(4), 10-10 1p | Publication status
46 | Alexander, E. S.,Martin, L. J.,Collins, M. H.,Kottyan, L. C.,Sucharew, H.,He, H.,Mukkada, V. A.,Succop, P. A.,Abonia, J. P.,Foote, H.,Eby, M. D.,Grotjan, T. M.,Greenler, A. J.,Dellon, E. S.,Demain, J. G.,Furuta, G. T.,Gurian, L. E.,Harley, J. B.,Hopp, R. J.,Kagalwalla, A.,Kaul, A.,Nadeau, K. C.,Noel, R. J.,Putnam, P. E.,von Tiehl, K. F.,Rothenberg, M. E. (2014). Twin and family studies reveal strong environmental and weaker genetic cues explaining heritability of eosinophilic esophagitis J Allergy Clin Immunol, 134(5), 1084-1092 e1 | Study design, Outcome
47 | Alexy, U.,Kersting, M.,Sichert-Hellert, W.,Manz, F.,Schoch, G. (1998). Energy intake and growth of 3- to 36-month-old German infants and children Ann Nutr Metab, 42(2), 68-74 | Study design
48 | Al-Farsi, Y. M.,Al-Sharbati, M. M.,Waly, M. I.,Al-Farsi, O. A.,Al-Shafaee, M. A.,Al-Khaduri, M. M.,Trivedi, M. S.,Deth, R. C. (2012). Effect of suboptimal breast-feeding on occurrence of autism: a case-control study Nutrition, 28(7-8), e27-32 | Study design
49 | Alho, O. P.,Koivu, M.,Sorri, M.,Rantakallio, P. (1990). Risk factors for recurrent acute otitis media and respiratory infection in infancy Int J Pediatr Otorhinolaryngol, 19(2), 151-61 | Outcome
50 | Alho, O. P.,Laara, E.,Oja, H. (1996). Public health impact of various risk factors for acute otitis media in northern Finland Am J Epidemiol, 143(11), 1149-56 | Outcome
51 | Alho, O. P.,Laara,,Oja, H. (1996). How should relative risk estimates for acute otitis media in children aged less than 2 years be perceived? J Clin Epidemiol, 49(1), 9-14 | Intervention/exposure
52 | Ali, M. B.,Ghenghesh, K. S.,Aissa, R. B.,Abuhelfaia, A.,Dufani, M. (2005). Etiology of childhood diarrhea in Zliten, Libya Saudi Med J, 26(11), 1759-65 | Study design, Participant health
53 | Al-Jassir, M. S.,El-Bashir, B. M.,Moizuddin, S. K. (2004). Surveillance of infant feeding practices in Riyadh city Ann Saudi Med, 24(2), 136-40 | Study design, Outcome
54 | Allen, J.,Hector, D. (2005). Benefits of breastfeeding New South Wales public health bulletin, 16(3-4), 42-46 | Study design
55 | Allen, L. H.,Rosado, J. L.,Casterline, J. E.,Martinez, H.,Lopez, P.,Munoz, E.,Black, A. K. (1995). Vitamin B-12 deficiency and malabsorption are highly prevalent in rural Mexican communities Am J Clin Nutr, 62(5), 1013-9 | Intervention/exposure
56 | Allen, N. B.,Lewinsohn, P. M.,Seeley, J. R. (1998). Prenatal and perinatal influences on risk for psychopathology in childhood and adolescence Dev Psychopathol, 10(3), 513-29 | Study design
57 | Alliet, P.,Scholtens, P.,Raes, M.,Hensen, K.,Jongen, H.,Rummens, J. L.,Boehm, G.,Vandenplas, Y. (2007). Effect of prebiotic galacto-oligosaccharide, long-chain fructo-oligosaccharide infant formula on serum cholesterol and triacylglycerol levels Nutrition, 23(10), 719-23 | Size of study groups
58 | Alm, B.,Aberg, N.,Erdes, L.,Mollborg, P.,Pettersson, R.,Norvenius, S. G.,Goksor, E.,Wennergren, G. (2009). Early introduction of fish decreases the risk of eczema in infants Arch Dis Child, 94(1), 11-5 | Intervention/exposure
59 | Alm, B.,Erdes, L.,Mollborg, P.,Pettersson, R.,Norvenius, S. G.,Aberg, N.,Wennergren, G. (2008). Neonatal antibiotic treatment is a risk factor for early wheezing Pediatrics, 121(4), 697-702 | Outcome
60 | Alm, B.,Norvenius, S. G.,Wennergren, G.,Lagercrantz, H.,Helweg-Larsen, K.,Irgens, L. M. (2000). Living conditions in early infancy in Denmark, Norway and Sweden 1992-95: results from the Nordic Epidemiological SIDS study Acta Paediatr, 89(2), 208-14 | Study design
61 | Alm, B.,Wennergren, G.,Norvenius, S. G.,Skjaerven, R.,Lagercrantz, H.,Helweg-Larsen, K.,Irgens, L. M. (2002). Breast feeding and the sudden infant death syndrome in Scandinavia, 1992-95 Arch Dis Child, 86(6), 400-2 | Outcome
62 | Almeida, R. M.,De Marins, V. M.,Valle, J. (1999). Breastfeeding, socio-economic conditions and nutritional status of children younger than 12 months in Brazil Ann Trop Paediatr, 19(3), 257-62 | Study design
63 | Al-Mousawi, M. S.,Lovel, H.,Behbehani, N.,Arifhodzic, N.,Woodcock, A.,Custovic, A. (2004). Asthma and sensitization in a community with low indoor allergen levels and low pet-keeping frequency J Allergy Clin Immunol, 114(6), 1389-94 | Outcome
64 | Almquist-Tangen, G.,Dahlgren, J.,Roswall, J.,Bergman, S.,Alm, B. (2013). Milk cereal drink increases BMI risk at 12 and 18 months, but formula does not Acta Paediatr, 102(12), 1174-9 | Intervention/exposure
65 | Al-Mustafa, Z. H.,Al-Madan, M.,Al-Majid, H. J.,Al-Muslem, S.,Al-Ateeq, S.,Al-Ali, A. K. (2007). Vitamin D deficiency and rickets in the Eastern Province of Saudi Arabia Ann Trop Paediatr, 27(1), 63-7 | Outcome
66 | Alper, C. M.,Winther, B.,Hendley, J. O.,Doyle, W. J. (2009). Cytokine polymorphisms predict the frequency of otitis media as a complication of rhinovirus and RSV infections in children Eur Arch Otorhinolaryngol, 266(2), 199-205 | Outcome
67 | Alper, C. M.,Winther, B.,Mandel, E. M.,Hendley, J. O.,Doyle, W. J. (2009). Rate of concurrent otitis media in upper respiratory tract infections with specific viruses Arch Otolaryngol Head Neck Surg, 135(1), 17-21 | Study design
68 | Al-Qaoud, N.,Prakash, P. (2009). Breastfeeding and obesity among Kuwaiti preschool children Medical Principles and Practice, 18(2), 111-117 | Study design
69 | Al-Qaoud, N.,Prakash, P. (2009). ‘Can breastfeeding and its duration determine the overweight status of Kuwaiti children at the age of 3-6 years?’ Eur J Clin Nutr, 63(8), 1041-3 | Study design
70 | Al-Shehri, M. A.,Sadeq, A.,Quli, K. (2005). Bronchiolitis in Abha, Southwest Saudi Arabia: viral etiology and predictors for hospital admission West Afr J Med, 24(4), 299-304 | Participant health
71 | Al-Shehri, S. S.,Knox, C. L.,Liley, H. G.,Cowley, D. M.,Wright, J. R.,Henman, M. G.,Hewavitharana, A. K.,Charles, B. G.,Shaw, P. N.,Sweeney, E. L.,Duley, J. A. (2015). Breastmilk-Saliva Interactions Boost Innate Immunity by Regulating the Oral Microbiome in Early Infancy PLoS One, 10(9), e0135047 | Intervention/exposure, Outcome
72 | Althaus, B. W. (1999). Growth patterns of Hispanic and Caucasian children #journal#, Ph.D.(#issue#), 105 p-105 p 1p | Publication status
73 | Altinkaynak, S.,Selimoglu, M. A.,Turgut, A.,Kilicaslan, B.,Ertekin, V. (2006). Breast-feeding duration and childhood acute leukemia and lymphomas in a sample of Turkish children Journal of Pediatric Gastroenterology and Nutrition, 42(5), 568-572 | Intervention/exposure
74 | Altucher, K.,Rasmussen, K. M.,Barden, E. M.,Habicht, J. P. (2005). Predictors of improvement in hemoglobin concentration among toddlers enrolled in the Massachusetts WIC Program J Am Diet Assoc, 105(5), 709-15 | Study design, Intervention/exposure
75 | Alvarado, B. E.,Zunzunegui, M. V.,Delisle, H.,Osorno, J. (2005). Growth trajectories are influenced by breast-feeding and infant health in an afro-colombian community J Nutr, 135(9), 2171-8 | Intervention/exposure
76 | Alvarado, R.,Zepeda, A.,Rivero, S.,Rico, N.,Lopez, S.,Diaz, S. (1999). Integrated maternal and infant health care in the postpartum period in a poor neighborhood in Santiago, Chile Stud Fam Plann, 30(2), 133-41 | Outcome
77 | Alves, J. G.,Figueira, F.,Nacul, L. C. (1999). Hospital induced malnutrition in infants: prevention by relactation Indian Pediatr, 36(5), 484-7 | Participant health
78 | Alves, J. G.,Figueiroa, J. N.,Meneses, J.,Alves, G. V. (2012). Breastfeeding protects against type 1 diabetes mellitus: a case-sibling study Breastfeed Med, 7(1), 25-8 | Outcome
79 | Amador, M.,Hermelo, M. P.,Canetti, J. E.,Consuegra, E. (1992). Adolescent mothers: do they breast-feed less? Acta Paediatr Hung, 32(3), 269-85 | Study design
80 | Amador-Licona, N.,Martinez-Cordero, C.,Guizar-Mendoza, J. M.,Malacara, J. M.,Hernandez, J.,Alcala, J. F. (2007). Catch-up growth in infants born small for gestational age--a longitudinal study J Pediatr Endocrinol Metab, 20(3), 379-86 | Study design
81 | Amaratunge, A.,Ekanayake, S. L. (1984). Rampant caries in Sri Lankan children. A pilot study Odontostomatol Trop, 7(3), 133-8 | Size of study groups
82 | Amigo, H.,Bustos, P.,Leone, C.,Radrigán, M. E. (2001). Community and international nutrition: Growth deficits in Chilean school children Journal of Nutrition, 131(2), 251-254 | Intervention/exposure
83 | Amorim Rde, J.,Coelho, A. F.,de Lira, P. I.,Lima Mde, C. (2014). Is breastfeeding protective for blood pressure in schoolchildren? A cohort study in northeast Brazil Breastfeed Med, 9(3), 149-56 | Outcome
84 | Ananthakrishnan, S.,Bhat, B. V.,Puri, R. K.,Srinivasan, S. (1992). Loose stools in the early neonatal period Indian Pediatr, 29(8), 1005-9 | Country
85 | Ancona, J.,Shaker, C. S.,Puhek, J.,Garland, J. S. (1998). Improving outcomes through a developmental approach to nipple feeding J Nurs Care Qual, 12(5), 1-4 | Study design
86 | Andersen, G. E. (1985). Changes in plasma lipoproteins from first day to third week of human life Prog Clin Biol Res, 188(#issue#), 87-91 | Study design
87 | Andersen, L. B.,Pipper, C. B.,Trolle, E.,Bro, R.,Larnkjaer, A.,Carlsen, E. M.,Molgaard, C.,Michaelsen, K. F. (2015). Maternal obesity and offspring dietary patterns at 9 months of age Eur J Clin Nutr, 69(6), 668-75 | Intervention/exposure
88 | Anderson, G. H.,Morson-Pasut, L. A.,Bryan, H.,Cleghorn, G.,Tanaka, P.,Yeung, D.,Zimmerman, B. (1985). Age of introduction of cow’s milk to infants J Pediatr Gastroenterol Nutr, 4(5), 692-8 | Study design
89 | Anderson, J. E.,Marks, J. S.,Park, T. K. (1984). Breast-feeding, birth interval, and infant health Pediatrics, 74(4 Pt 2), 695-701 | Study design
90 | Anderson, J.,Hayes, D.,Chock, L. (2014). Characteristics of overweight and obesity at age two and the association with breastfeeding in Hawai’i Women, Infants, and Children (WIC) participants Matern Child Health J, 18(10), 2323-31 | Outcome
91 | Anderson, K. (2001). The sweet and sour of pediatric caries CDS Rev, 94(7), 16-9 | Study design
92 | Anderson, L. J.,Parker, R. A.,Strikas, R. A.,Farrar, J. A.,Gangarosa, E. J.,Keyserling, H. L.,Sikes, R. K. (1988). Day-care center attendance and hospitalization for lower respiratory tract illness Pediatrics, 82(3), 300-308 | Outcome
93 | Anderson, P. O.,Valdes, V. (2015). Variation of milk intake over time: clinical and pharmacokinetic implications Breastfeed Med, 10(3), 142-4 | Study design, Outcome
94 | Andersson, M.,Aeberli, I.,Wust, N.,Piacenza, A. M.,Bucher, T.,Henschen, I.,Haldimann, M.,Zimmermann, M. B. (2010). The Swiss iodized salt program provides adequate iodine for school children and pregnant women, but weaning infants not receiving iodine-containing complementary foods as well as their mothers are iodine deficient J Clin Endocrinol Metab, 95(12), 5217-24 | Study design, Intervention/exposure
95 | Andreev, A.,Arjas, E. (1998). Acute middle ear infection in small children: a Bayesian analysis using multiple time scales Lifetime Data Anal, 4(2), 121-37 | Study design
96 | Andres, A.,Casey, P. H.,Cleves, M. A.,Badger, T. M. (2013). Body fat and bone mineral content of infants fed breast milk, cow’s milk formula, or soy formula during the first year of life J Pediatr, 163(1), 49-54 | Intervention/exposure
97 | Andres, A.,Cleves, M. A.,Bellando, J. B.,Pivik, R. T.,Casey, P. H.,Badger, T. M. (2012). Developmental status of 1-year-old infants fed breast milk, cow’s milk formula, or soy formula Pediatrics, 129(6), 1134-40 | Intervention/exposure
98 | Anfield, L. (1985). Nutrition in the first year Midwife Health Visit Community Nurse, 21(5), 161-4 | Study design
99 | Angelsen, N. K.,Vik, T.,Jacobsen, G.,Bakketeig, L. S. (2001). Breast feeding and cognitive development at age 1 and 5 years Arch Dis Child, 85(3), 183-8 | Outcome
100 | Angulo, N.,de Szarvas, S. B.,Guevara, H.,Mathison, Y.,González, D.,Hernández, A. (2014). Lifestyle of a group of obese children located in Valencia Salus, 18(1), 25-31 | Language
101 | Angurana, S. K.,Angurana, R. S.,Mahajan, G.,Kumar, N.,Mahajan, V. (2014). Prevalence of vitamin D deficiency in apparently healthy children in north India J Pediatr Endocrinol Metab, 27(11-12), 1151-6 | Country
102 | Anholm, P. C. (1986). Breastfeeding: a preventive approach to health care in infancy Issues Compr Pediatr Nurs, 9(1), 1-10 | Study design
103 | Aniansson, G.,Alm, B.,Andersson, B.,Hakansson, A.,Larsson, P.,Nylen, O.,Peterson, H.,Rigner, P.,Svanborg, M.,Sabharwal, H.,et al, (1994). A prospective cohort study on breast-feeding and otitis media in Swedish infants Pediatr Infect Dis J, 13(3), 183-8 | Outcome
104 | Annamalay, A. A.,Khoo, S. K.,Jacoby, P.,Bizzintino, J.,Zhang, G.,Chidlow, G.,Lee, W. M.,Moore, H. C.,Harnett, G. B.,Smith, D. W.,Gern, J. E.,LeSouef, P. N.,Laing, I. A.,Lehmann, D. (2012). Prevalence of and risk factors for human rhinovirus infection in healthy aboriginal and non-aboriginal Western Australian children Pediatr Infect Dis J, 31(7), 673-9 | Outcome
105 | Ansari-Moghaddam, A.,Sadeghi-Bojd, S.,Imani, M.,Movahedinia, S.,Pourrashidi, A.,Mohammadi, M. (2014). A multivariate analysis of factors associated with infant mortality in South-East of Iran J Pak Med Assoc, 64(10), 1123-6 | Outcome
106 | Apostolopoulos, K.,Xenelis, J.,Tzagaroulakis, A.,Kandiloros, D.,Yiotakis, J.,Papafragou, K. (1998). The point prevalence of otitis media with effusion among school children in Greece International Journal of Pediatric Otorhinolaryngology, 44(3), 207-214 | Study design
107 | Apps, J. R.,Beattie, R. M. (2009). Cow’s milk allergy in children BMJ, 339(#issue#), b2275 | Study design
108 | Araujo, C. L.,Victora, C. G.,Hallal, P. C.,Gigante, D. P. (2006). Breastfeeding and overweight in childhood: evidence from the Pelotas 1993 birth cohort study Int J Obes (Lond), 30(3), 500-6 | Outcome
109 | Araujo, D. S.,Marquezin, M. C.,Barbosa, T. S.,Gaviao, M. B.,Castelo, P. M. (2015). Evaluation of masticatory parameters in overweight and obese children Eur J Orthod, #volume#(#issue#), #Pages# | Study design
110 | Arica, S.,Arica, V.,Dag, H.,Kaya, A.,Hatipoglu, S.,Fenercioglu, A.,Karatekin, G. (2011). Serum zinc levels in children of 0-24 months diagnosed with pneumonia admitted to our clinic International Journal of Clinical and Experimental Medicine, 4(3), 227-233 | Participant health, Intervention/exposure, Size of study groups
111 | Arimond, M.,Daelmans, B.,Dewey, K. (2008). Indicators for feeding practices in children Lancet, 371(9612), 541-2 | Study design
112 | Aris, I. M.,Soh, S. E.,Tint, M. T.,Saw, S. M.,Rajadurai, V. S.,Godfrey, K. M.,Gluckman, P. D.,Yap, F.,Chong, Y. S.,Lee, Y. S. (2015). Associations of infant milk feed type on early postnatal growth of offspring exposed and unexposed to gestational diabetes in utero Eur J Nutr, #volume#(#issue#), #Pages# | Intervention/exposure
113 | Arlette, J. P. (1982). Zinc deficiency in children Int J Dermatol, 21(8), 447-8 | Study design
114 | Armstrong, J.,Reilly, J. J. (2002). Breastfeeding and lowering the risk of childhood obesity Lancet, 359(9322), 2003-4 | Outcome
115 | Arnon, S. S.,Damus, K.,Thompson, B.,Midura, T. F.,Chin, J. (1982). Protective role of human milk against sudden death from infant botulism J Pediatr, 100(4), 568-73 | Size of study groups, Intervention/exposure
116 | Aronsson, C. A.,Lee, H. S.,Koletzko, S.,Uusitalo, U.,Yang, J.,Virtanen, S. M.,Liu, E.,Lernmark, A.,Norris, J. M.,Agardh, D. (2015). Effects of Gluten Intake on Risk of Celiac Disease: A Case-Control Study on a Swedish Birth Cohort Clin Gastroenterol Hepatol, #volume#(#issue#), #Pages# | Outcome
117 | Arora, N. K.,Bhan, M. K. (1991). Nutritional management of acute diarrhea Indian J Pediatr, 58(6), 763-7 | Country, Study design
118 | Arshad, S. H.,Bateman, B.,Matthews, S. M. (2003). Primary prevention of asthma and atopy during childhood by allergen avoidance in infancy: a randomised controlled study Thorax, 58(6), 489-93 | Intervention/exposure
119 | Arshad, S. H.,Bateman, B.,Sadeghnejad, A.,Gant, C.,Matthews, S. M. (2007). Prevention of allergic disease during childhood by allergen avoidance: the Isle of Wight prevention study J Allergy Clin Immunol, 119(2), 307-13 | Intervention/exposure
120 | Arton M (1985). Breast feeding--a life-saver in the Third World Midwives Chron, 98(#issue#), 200-1 | Study design
121 | Aryayev, N.,Kukushkin, V. (2002). The perinatal risk factors of sudden infant death syndrome Perinatology, 4(3), 125-133 | Publication status
122 | Aryayev, N.,Kukushkin, V.,Nepomyashcha, V. (2001). The significance of ante- and perinatal periods for formation of risk of sudden infant death syndrome Ginekologia polska, 72(12), 931-939 | Outcome
123 | Asaka, A.,Imaizumi, Y.,Inouye, E. (1981). Analysis of multiple births in Japan. V. Effects of gestational age, maternal age and other factors on growth rate of weight in twins Jinrui Idengaku Zasshi, 26(2), 83-90 | Study design
124 | Ascher, H.,Krantz, I.,Rydberg, L.,Nordin, P.,Kristiansson, B. (1997). Influence of infant feeding and gluten intake on coeliac disease Arch Dis Child, 76(2), 113-7 | Size of study groups
125 | Asha Bai, P. V.,Leela, M.,Subramaniam, V. R. (1980). Adequacy of breast milk for optimal growth of infants Trop Geogr Med, 32(2), 158-62 | Country
126 | Ashraf, A. P.,Eason, N. B.,Kabagambe, E. K.,Haritha, J.,Meleth, S.,McCormick, K. L. (2010). Dietary iron intake in the first 4 months of infancy and the development of type 1 diabetes: A pilot study Diabetology and Metabolic Syndrome, 2(1), #Pages# | Study design
127 | Askie, L.,Martin, A.,Espinoza, D.,Campbell, K.,Daniels, L. A.,Hesketh, K.,Margarey, A.,Rissel, C.,Taylor, B.,Taylor, R.,Wen, L. M.,Baur, L. A. (2014). What does the EPOCH (early prevention of obesity in childhood) prospective meta-analysis tell us about early life obesity prevention? Obesity research & clinical practice, 8(#issue#), 3-4 | Publication status
128 | Assuncao, M. L.,Ferreira, H. S.,Coutinho, S. B.,Santos, L. M.,Horta, B. L. (2015). Protective effect of breastfeeding against overweight can be detected as early as the second year of life: a study of children from one of the most socially-deprived areas of Brazil J Health Popul Nutr, 33(1), 85-91 | Study design, Intervention/exposure
129 | Astarita, C.,Harris, R. I.,de Fusco, R.,Franzese, A.,Biscardi, D.,Mazzacca, F. R.,Altucci, P. (1988). An epidemiological study of atopy in children Clin Allergy, 18(4), 341-50 | Study design
130 | Atkins, L. A.,McNaughton, S. A.,Campbell, K. J.,Szymlek-Gay, E. A. (2015). Iron intakes of Australian infants and toddlers: findings from the Melbourne Infant Feeding, Activity and Nutrition Trial (InFANT) Program Br J Nutr, #volume#(#issue#), 1-9 | Outcome
131 | Atladottir, H.,Thorsdottir, I. (2000). Energy intake and growth of infants in Iceland-a population with high frequency of breast-feeding and high birth weight Eur J Clin Nutr, 54(9), 695-701 | Intervention/exposure
132 | Auerbach, K. G.,Renfrew, M. J.,Minchin, M. (1991). Infant feeding comparisons: a hazard to infant health? J Hum Lact, 7(2), 63-8 | Study design
133 | Auestad, N.,Halter, R.,Hall, R. T.,Blatter, M.,Bogle, M. L.,Burks, W.,Erickson, J. R.,Fitzgerald, K. M.,Dobson, V.,Innis, S. M.,Singer, L. T.,Montalto, M. B.,Jacobs, J. R.,Qiu, W.,Bornstein, M. H. (2001). Growth and development in term infants fed long-chain polyunsaturated fatty acids: a double-masked, randomized, parallel, prospective, multivariate study Pediatrics, 108(2), 372-81 | Intervention/exposure
134 | Auestad, N.,Montalto, M. B.,Hall, R. T.,Fitzgerald, K. M.,Wheeler, R. E.,Connor, W. E.,Neuringer, M.,Connor, S. L.,Taylor, J. A.,Hartmann, E. E. (1997). Visual acuity, erythrocyte fatty acid composition, and growth in term infants fed formulas with long chain polyunsaturated fatty acids for one year. Ross Pediatric Lipid Study Pediatr Res, 41(1), 1-10 | Intervention/exposure
135 | Auestad, N.,Scott, D. T.,Janowsky, J. S.,Jacobsen, C.,Carroll, R. E.,Montalto, M. B.,Halter, R.,Qiu, W.,Jacobs, J. R.,Connor, W. E.,Connor, S. L.,Taylor, J. A.,Neuringer, M.,Fitzgerald, K. M.,Hall, R. T. (2003). Visual, cognitive, and language assessments at 39 months: a follow-up study of children fed formulas containing long-chain polyunsaturated fatty acids to 1 year of age Pediatrics, 112(3 Pt 1), e177-83 | Intervention/exposure
136 | Auricchio, S.,Follo, D.,de Ritis, G.,Giunta, A.,Marzorati, D.,Prampolini, L.,Ansaldi, N.,Levi, P.,Dall’Olio, D.,Bossi, A.,et al, (1983). Does breast feeding protect against the development of clinical symptoms of celiac disease in children? J Pediatr Gastroenterol Nutr, 2(3), 428-33 | Outcome
137 | Avoa, A.,Fischer, P. R. (1990). The influence of perinatal instruction about breast-feeding on neonatal weight loss Pediatrics, 86(2), 313-5 | Country
138 | Awasthi, S.,Misra, P. K.,Malik, G. K. (1987). Adequacy of breast milk Indian Pediatr, 24(10), 873-7 | Country
139 | Axelsson, I. E.,Ivarsson, S. A.,Raiha, N. C. (1989). Protein intake in early infancy: effects on plasma amino acid concentrations, insulin metabolism, and growth Pediatr Res, 26(6), 614-7 | Size of study groups, Intervention/exposure
140 | Axelsson, I.,Borulf, S.,Righard, L.,Raiha, N. (1987). Protein and energy intake during weaning: I. Effects on growth Acta Paediatr Scand, 76(2), 321-7 | Size of study groups
141 | Ayatollahi, S. M.,Sharafi, Z.,Haem, E. (2015). Child Weight Growth Chart and Its Associated Factors in Birth Cohort of Maku Using a Growth Curve Model and LMS Method Glob J Health Sci, 7(6), 44045 | Size of study groups
142 | Aydemir, G.,Ozkurt, F. E. (2011). Otitis media with effusion in primary schools in Princes’ Islands, Istanbul: Prevalence and risk factors Journal of International Medical Research, 39(3), 866-872 | Study design
143 | Ayer, J. G.,Belousova, E.,Harmer, J. A.,David, C.,Marks, G. B.,Celermajer, D. S. (2011). Maternal cigarette smoking is associated with reduced high-density lipoprotein cholesterol in healthy 8-year-old children Eur Heart J, 32(19), 2446-53 | Intervention/exposure
144 | Azizi, B. H.,Zulkifli, H. I.,Kasim, M. S. (1995). Protective and risk factors for acute respiratory infections in hospitalized urban Malaysian children: a case control study Southeast Asian J Trop Med Public Health, 26(2), 280-5 | Study design, Size of study groups
145 | Babeely, K.,Kaste, L. M.,Husain, J.,Behbehani, J.,al-Za’abi, F.,Maher, T. C.,Tavares, M.,Soparkar, P.,DePaola, P. (1989). Severity of nursing-bottle syndrome and feeding patterns in Kuwait Community Dent Oral Epidemiol, 17(5), 237-9 | Study design, Intervention/exposure
146 | Backon, J. (1984). Prolonged breast feeding as a prophylaxis for recurrent otitis media: relevance of prostaglandins Med Hypotheses, 13(2), 161 | Publication status
147 | Bacopoulou, F.,Veltsista, A.,Vassi, I.,Gika, A.,Lekea, V.,Priftis, K.,Bakoula, C. (2009). Can we be optimistic about asthma in childhood? A Greek cohort study J Asthma, 46(2), 171-4 | Intervention/exposure
148 | Badger, T. (2013). Effects of soy infant formula on growth and development in the first year of life Food Nutr Bull, 34(2), 252-3 | Study design, Intervention/exposure
149 | Badger, Thomas M. (2014). STUDY SUGGESTS SOY FORMULA MAY BE GOOD CHOICE FOR SOME INFANTS JAAPA: Journal of the American Academy of Physician Assistants (Lippincott Williams & Wilkins), 27(5), 1-3 3p | Publication status
150 | Bagnoli, F.,Casucci, M.,Toti, S.,Cecchi, S.,Iurato, C.,Coriolani, G.,Tiezzi, M.,Vispi, L. (2013). Is vitamin D supplementation necessary in healthy full-term breastfed infants? A follow-up study of bone mineralization in healthy full-term infants with and without supplemental vitamin D Minerva Pediatr, 65(3), 253-60 | Size of study groups
151 | Baheiraei, A.,Ardsetani, N.,Ghazizadeh, Sh (2001). Effects of progestogen-only contraceptives on breast-feeding and infant growth International Journal of Gynecology and Obstetrics, 74(2), 203-205 | Intervention/exposure
152 | Bahl, R.,Frost, C.,Kirkwood, B. R.,Edmond, K.,Martines, J.,Bhandari, N.,Arthur, P. (2005). Infant feeding patterns and risks of death and hospitalization in the first half of infancy: multicentre cohort study Bull World Health Organ, 83(6), 418-26 | Outcome
153 | Bai, K. I.,Sastry, V. N.,Reddy, C. C. (1981). A comparative study of feeding pattern of infants in rural and urban areas Indian J Pediatr, 48(392), 277-80 | Country
154 | Bailey W (1981). Malnutrition among babies born to adolescent mothers West Indian Med J, 30(#issue#), 72-6 | Participant health, Outcomes
155 | Bailey, P.,Tsui, A. O.,Janowitz, B.,Dominik, R.,Araujo, L. (1990). A study of infant mortality and causes of death in a rural north-east Brazilian community J Biosoc Sci, 22(3), 349-63 | Outcome
156 | Bailey, W. (1981). Clinical undernutrition in the Kingston/St Andrew metropolitan area: 1967-1976 Soc Sci Med D, 15(4), 471-7 | Study design, Outcome
157 | Bainbridge, J. (2008). Higher IQs for breastfed babies British Journal of Midwifery, 16(6), 394-394 1p | Study design
158 | Bainbridge, J. (2009). Breastfed babies less likely to become overweight children British Journal of Midwifery, 17(6), 393-393 1p | Study design
159 | Baird, J.,Poole, J.,Robinson, S.,Marriott, L.,Godfrey, K.,Cooper, C.,Inskip, H.,Law, C. (2008). Milk feeding and dietary patterns predict weight and fat gains in infancy Paediatr Perinat Epidemiol, 22(6), 575-86 | Outcome
160 | Baker, D.,Taylor, H.,Henderson, J. (1998). Inequality in infant morbidity: Causes and consequences in England in the 1990s Journal of Epidemiology and Community Health, 52(7), 451-458 | Outcome
161 | Baker, D.,Taylor, H.,Henderson, J. (1998). Inequality in infant morbidity: causes and consequences in England in the 1990s. ALSPAC Study Team. Avon Longitudinal Study of Pregnancy and Childhood J Epidemiol Community Health, 52(7), 451-8 | Outcome
162 | Baker, J. L.,Michaelsen, K. F.,Rasmussen, K. M.,Sorensen, T. I. (2004). Maternal prepregnant body mass index, duration of breastfeeding, and timing of complementary food introduction are associated with infant weight gain Am J Clin Nutr, 80(6), 1579-88 | Outcome
163 | Baker, R. J.,Hertz-Picciotto, I.,Dostal, M.,Keller, J. A.,Nozicka, J.,Kotesovec, F.,Dejmek, J.,Loomis, D.,Sram, R. J. (2006). Coal home heating and environmental tobacco smoke in relation to lower respiratory illness in Czech children, from birth to 3 years of age Environ Health Perspect, 114(7), 1126-32 | Outcome
164 | Bakker, E. C.,van Houwelingen, A. C.,Hornstra, G. (1999). Early nutrition, essential fatty acid status and visual acuity of term infants at 7 months of age Eur J Clin Nutr, 53(11), 872-9 | Study design
165 | Balaban, G.,Motta, M. E.,Silva, G. A. (2010). Early weaning and other potential risk factors for overweight among preschool children Clinics (Sao Paulo), 65(2), 181-7 | Study design
166 | Balasubramanian S (2011). Vitamin D deficiency in breastfed infants & the need for routine vitamin D supplementation Indian J Med Res, 133(#issue#), 250-2 | Study design
167 | Ball, T. M.,Wright, A. L. (1999). Health care costs of formula-feeding in the first year of life Pediatrics, 103(4 Pt 2), 870-6 | Outcome
168 | Bammann, K.,Peplies, J.,De Henauw, S.,Hunsberger, M.,Molnar, D.,Moreno, L. A.,Tornaritis, M.,Veidebaum, T.,Ahrens, W.,Siani, A. (2014). Early life course risk factors for childhood obesity: the IDEFICS case-control study PLoS One, 9(2), e86914 | Study design
169 | Bandara, T.,Hettiarachchi, M.,Liyanage, C.,Amarasena, S. (2015). Current infant feeding practices and impact on growth in babies during the second half of infancy J Hum Nutr Diet, 28(4), 366-74 | Study design
170 | Bandoli, G.,von Ehrenstein, O. S.,Flores, M. E.,Ritz, B. (2015). Breastfeeding and Asthmatic Symptoms in The Offspring of Latinas: The Role of Maternal Nativity J Immigr Minor Health, 17(6), 1739-45 | Study design
171 | Bandurska-Stankiewicz, E.,Rutkowska, J. (2008). Environmental risk factors for type 1 diabetes in the north of Poland Diabetologia Doswiadczalna i Kliniczna, 8(2), 81-84 | Study design
172 | Banerji, A.,Greenberg, D.,White, L. F.,Macdonald, W. A.,Saxton, A.,Thomas, E.,Sage, D.,Mamdani, M.,Lanctot, K. L.,Mahony, J. B.,Dingle, M.,Roberts, A. (2009). Risk factors and viruses associated with hospitalization due to lower respiratory tract infections in Canadian Inuit children : a case-control study Pediatr Infect Dis J, 28(8), 697-701 | Outcome
173 | Bankel, M.,Robertson, A.,Kohler, B. (2011). Carious lesions and caries risk predictors in a group of Swedish children 2 to 3 years of age. One year observation Eur J Paediatr Dent, 12(4), 215-9 | Study design, Size of study groups
174 | Baranowski, T.,Bryan, G. T.,Harrison, J. A.,Rassin, D. K.,Greaves, K. A.,Baranowski, J. H. (1992). Height, infant-feeding practices and cardiovascular functioning among 3 or 4 year old children in three ethnic groups J Clin Epidemiol, 45(5), 513-8 | Study design
175 | Baranowski, T.,Bryan, G. T.,Rassin, D. K.,Harrison, J. A.,Henske, J. C. (1990). Ethnicity, infant-feeding practices, and childhood adiposity J Dev Behav Pediatr, 11(5), 234-9 | Study design
176 | Barge, K. (2007). Breast-feeding doesn’t contribute to dental caries J Dent Hyg, 81(4), 69 | Study design
177 | Barness LA (1983). Impact of breast feeding--obviating problems J Fla Med Assoc, 70(#issue#), 831-2 | Study design
178 | Baron, S.,Turck, D.,Leplat, C.,Merle, V.,Gower-Rousseau, C.,Marti, R.,Yzet, T.,Lerebours, E.,Dupas, J. L.,Debeugny, S.,Salomez, J. L.,Cortot, A.,Colombel, J. F. (2005). Environmental risk factors in paediatric inflammatory bowel diseases: a population based case control study Gut, 54(3), 357-63 | Outcome
179 | Barreto, B. A.,Sole, D. (2014). Prevalence of asthma and associated factors in adolescents living in Belem (Amazon region), Para, Brazil Allergol Immunopathol (Madr), 42(5), 427-32 | Study design
180 | Barros, F. C.,Rossello, J. L.,Matijasevich, A.,Dumith, S. C.,Barros, A. J.,dos Santos, I. S.,Mota, D.,Victora, C. G. (2012). Gestational age at birth and morbidity, mortality, and growth in the first 4 years of life: findings from three birth cohorts in Southern Brazil BMC Pediatr, 12(#issue#), 169 | Intervention/exposure
181 | Barros, F. C.,Semer, T. C.,Tonioli Filho, S.,Tomasi, E.,Victora, C. G. (1995). The impact of lactation centres on breastfeeding patterns, morbidity and growth: a birth cohort study Acta Paediatr, 84(11), 1221-6 | Outcome
182 | Barros, F. C.,Victora, C. G.,Morris, S. S.,Halpern, R.,Horta, B. L.,Tomasi, E. (1997). Breast feeding, pacifier use and infant development at 12 months of age: a birth cohort study in Brazil Paediatr Perinat Epidemiol, 11(4), 441-50 | Outcome
183 | Barros, F. C.,Victora, C. G.,Vaughan, J. P.,Tomasi, E.,Horta, B. L.,Cesar, J. A.,Menezes, M. B.,Halpern, R.,Post, C. L.,del Mar Garcia, M. (2001). The epidemiological transition in maternal and child health in a Brazilian city, 1982-93: a comparison of two population-based cohorts Paediatr Perinat Epidemiol, 15(1), 4-11 | Outcome
184 | Barroso, C. S.,Roncancio, A.,Hinojosa, M. B.,Reifsnider, E. (2012). The association between early childhood overweight and maternal factors Child Obes, 8(5), 449-54 | Study design, Size of study groups
185 | Barsam, F. J.,Borges, G. S.,Severino, A. B.,de Mello, L. M.,da Silva, A. S.,Nunes, A. A. (2013). Factors associated with community-acquired pneumonia in hospitalised children and adolescents aged 6 months to 13 years old Eur J Pediatr, 172(4), 493-9 | Outcome
186 | Bartels, M.,van Beijsterveldt, C. E.,Boomsma, D. I. (2009). Breastfeeding, maternal education and cognitive function: a prospective study in twins Behav Genet, 39(6), 616-22 | Outcome
187 | Bartok, C. J. (2011). Babies fed breastmilk by breast versus by bottle: a pilot study evaluating early growth patterns Breastfeed Med, 6(3), 117-24 | Size of study groups
188 | Barton, S. J.,Howard, P. K.,Rayens, M. K. (2002). The effects of infant feeding decisions on infant growth J Spec Pediatr Nurs, 7(2), 64-70 | Size of study groups
189 | Basheer, R. (1988). Breast is best Nurs J India, 79(7), 180, 190 | Study design
190 | Bassal, R.,Reisfeld, A.,Nissan, I.,Agmon, V.,Taran, D.,Schemberg, B.,Cohen, D.,Shohat, T. (2014). Risk factors for sporadic infection with Salmonella Infantis: a matched case-control study Epidemiol Infect, 142(4), 820-5 | Size of study groups, Outcome
191 | Batstra, L.,Neeleman, J.,Hadders-Algra, M. (2003). Can breast feeding modify the adverse effects of smoking during pregnancy on the child’s cognitive development? J Epidemiol Community Health, 57(6), 403-4 | Study design
192 | Bauer, G.,Ewald, L. S.,Hoffman, J.,Dubanoski, R. (1991). Breastfeeding and cognitive development of three-year-old children Psychol Rep, 68(3 Pt 2), 1218 | Study design
193 | Baumgartner, C. (1984). Psychomotor and social development of breast-fed and bottle-fed babies during their first year of life Acta Paediatr Hung, 25(4), 409-17 | Size of study groups
194 | Baur, L. A.,O’Connor, J.,Pan, D. A.,Kriketos, A. D.,Storlien, L. H. (1998). The fatty acid composition of skeletal muscle membrane phospholipid: its relationship with the type of feeding and plasma glucose levels in young children Metabolism, 47(1), 106-12 | Size of study groups, Intervention/exposure
195 | Baur, L. A.,O’Connor, J.,Pan, D. A.,Wu, B. J.,O’Connor, M. J.,Storlien, L. H. (2000). Relationships between the fatty acid composition of muscle and erythrocyte membrane phospholipid in young children and the effect of type of infant feeding Lipids, 35(1), 77-82 | Size of study groups, Intervention/exposure
196 | Baxter-Jones, A. D.,Cardy, A. H.,Helms, P. J.,Phillips, D. O.,Smith, W. C. (1999). Influence of socioeconomic conditions on growth in infancy: the 1921 Aberdeen birth cohort Arch Dis Child, 81(1), 5-9 | Outcome
197 | Bayley, T. M.,Alasmi, M.,Thorkelson, T.,Jones, P. J.,Corcoran, J.,Krug-Wispe, S.,Tsang, R. C. (2002). Longer term effects of early dietary cholesterol level on synthesis and circulating cholesterol concentrations in human infants Metabolism, 51(1), 25-33 | Size of study groups
198 | Bayley, T. M.,Alasmi, M.,Thorkelson, T.,Krug-Wispe, S.,Jones, P. J.,Bulani, J. L.,Tsang, R. C. (1998). Influence of formula versus breast milk on cholesterol synthesis rates in four-month-old infants Pediatr Res, 44(1), 60-7 | Size of study groups
199 | Baylis, J. M.,Leeds, A. R.,Challacombe, D. N. (1983). Persistent nausea and food aversions in pregnancy. A possible association with cow’s milk allergy in infants Clin Allergy, 13(3), 263-9 | Size of study groups
200 | Bayraktar, S.,Bayraktar, S. T.,Selcuk, N.,Emiroglu, H.,Elevli, M. (2006). Lipid and lipoprotein profile of breast fed, formula fed or mixed-fed 0-6-month-old babies International Pediatrics, 21(2), 84-90 | Study design
201 | Beath, K. J. (2007). Infant growth modelling using a shape invariant model with random effects Stat Med, 26(12), 2547-64 | Outcome
202 | Beauchamp, J. N.,Gaboury, I.,Ni, A.,Boland, M. P.,Mac, K. D. R. (2011). Solid-food introduction in infants diagnosed as having a cow’s-milk protein-induced enterocolitis Journal of Pediatric Gastroenterology and Nutrition, 52(5), 639-643 | Participant health, Intervention/exposure
203 | Beaudry, M.,Dufour, R.,Marcoux, S. (1995). Reaction between infant feeding and infections during the first six months of life Journal of Pediatrics, 126(2), 191-197 | Study design
204 | Beaudry, M.,Dufour, R.,Marcoux, S. (1995). Relation between infant feeding and infections during the first six months of life J Pediatr, 126(2), 191-7 | Study design
205 | Beaver, K. M.,Vaughn, M. G.,DeLisi, M.,Higgins, G. E. (2010). The biosocial correlates of neuropsychological deficits: results from the national longitudinal study of adolescent health Int J Offender Ther Comp Criminol, 54(6), 878-94 | Outcome
206 | Becher, J. C.,Bhushan, S. S.,Lyon, A. J. (2012). Unexpected collapse in apparently healthy newborns--a prospective national study of a missing cohort of neonatal deaths and near-death events Arch Dis Child Fetal Neonatal Ed, 97(1), F30-4 | Study design
207 | Beebe, D. W.,Rausch, J.,Byars, K. C.,Lanphear, B.,Yolton, K. (2012). Persistent snoring in preschool children: predictors and behavioral and developmental correlates Pediatrics, 130(3), 382-9 | Intervention/exposure, Outcome
208 | Beentjes VE,Weerheijm KL,Groen HJ (2002). Factors involved in the aetiology of molar-incisor hypomineralisation (MIH) Eur J Paediatr Dent, 3(#issue#), 9-13 | Study design, Size of study groups
209 | Beilin, L.,Huang, R. C. (2008). Childhood obesity, hypertension, the metabolic syndrome and adult cardiovascular disease Clin Exp Pharmacol Physiol, 35(4), 409-11 | Study design
210 | Bekkers, M. B.,Brunekreef, B.,Smit, H. A.,Kerkhof, M.,Koppelman, G. H.,Oldenwening, M.,Wijga, A. H. (2011). Early-life determinants of total and HDL cholesterol concentrations in 8-year-old children; the PIAMA birth cohort study PLoS One, 6(9), e25533 | Outcome
211 | Belfort, M. B.,Rifas-Shiman, S. L.,Kleinman, K. P.,Guthrie, L. B.,Bellinger, D. C.,Taveras, E. M.,Gillman, M. W.,Oken, E. (2013). Infant feeding and childhood cognition at ages 3 and 7 years: Effects of breastfeeding duration and exclusivity JAMA Pediatr, 167(9), 836-44 | Outcome
212 | Belfort, M. B.,Rifas-Shiman, S. L.,Rich-Edwards, J. W.,Kleinman, K. P.,Oken, E.,Gillman, M. W. (2008). Infant growth and child cognition at 3 years of age Pediatrics, 122(3), e689-95 | Intervention/exposure
213 | Ben, X. M.,Zhou, X. Y.,Zhao, W. H.,Yu, W. L.,Pan, W.,Zhang, W. L.,Wu, S. M.,Van Beusekom, C. M.,Schaafsma, A. (2004). Growth and development of term infants fed with milk with long-chain polyunsaturated fatty acid supplementation Chinese Medical Journal, 117(8), 1268-1270 | Size of study groups, Intervention/exposure
214 | Bener, A.,Alsaied, A.,Al-Ali, M.,Al-Kubaisi, A.,Basha, B.,Abraham, A.,Guiter, G.,Mian, M. (2009). High prevalence of vitamin D deficiency in type 1 diabetes mellitus and healthy children Acta Diabetol, 46(3), 183-9 | Study design
215 | Bener, A.,Denic, S.,Galadari, S. (2001). Longer breast-feeding and protection against childhood leukaemia and lymphomas Eur J Cancer, 37(2), 234-8 | Intervention/exposure
216 | Bener, A.,Hoffmann, G. F.,Afify, Z.,Rasul, K.,Tewfik, I. (2008). Does prolonged breastfeeding reduce the risk for childhood leukemia and lymphomas? Minerva Pediatr, 60(2), 155-61 | Outcome
217 | Benn, C. S.,Wohlfahrt, J.,Aaby, P.,Westergaard, T.,Benfeldt, E.,Michaelsen, K. F.,Bjorksten, B.,Melbye, M. (2004). Breastfeeding and risk of atopic dermatitis, by parental history of allergy, during the first 18 months of life Am J Epidemiol, 160(3), 217-23 | Intervention/exposure
218 | Bennett, K. E.,Haggard, M. P. (1998). Accumulation of factors influencing children’s middle ear disease: risk factor modelling on a large population cohort J Epidemiol Community Health, 52(12), 786-93 | Study design, Outcome
219 | Berger, R.,Hadziselimovic, F.,Just, M.,Reigel, P. (1983). Effect of feeding human milk on nosocomial rotavirus infections in an infants ward Dev Biol Stand, 53(#issue#), 219-28 | Study design, Participant health
220 | Bergmann, K. E.,Bergmann, R. L.,Von Kries, R.,Bohm, O.,Richter, R.,Dudenhausen, J. W.,Wahn, U. (2003). Early determinants of childhood overweight and adiposity in a birth cohort study: role of breast-feeding Int J Obes Relat Metab Disord, 27(2), 162-72 | Intervention/exposure
221 | Bergmann, R. L.,Bergler, H.,Moshoudis, E.,Bergmann, K. E.,Lachmann, E. (1988). Prevention of iron deficiency of breast-fed babies by using suitable additional food, a prospective, controlled study Monatsschrift fur Kinderheilkunde, 136(#issue#), 491 | Language
222 | Bergmann, R. L.,Bergmann, K. E.,Lau-Schadensdorf, S.,Luck, W.,Dannemann, A.,Bauer, C. P.,Dorsch, W.,Forster, J.,Schmidt, E.,Schulz, J.,et al, (1994). Atopic diseases in infancy. The German multicenter atopy study (MAS-90) Pediatr Allergy Immunol, 5(6 Suppl), 19-25 | Intervention/exposure
223 | Bergmann, R. L.,Diepgen, T. L.,Kuss, O.,Bergmann, K. E.,Kujat, J.,Dudenhausen, J. W.,Wahn, U. (2002). Breastfeeding duration is a risk factor for atopic eczema Clin Exp Allergy, 32(2), 205-9 | Outcome
224 | Bergmann, R. L.,Edenharter, G.,Bergmann, K. E.,Lau, S.,Wahn, U. (2000). Socioeconomic status is a risk factor for allergy in parents but not in their children Clin Exp Allergy, 30(12), 1740-5 | Outcome
225 | Bergmann, R. L.,Haschke-Becher, E.,Klassen-Wigger, P.,Bergmann, K. E.,Richter, R.,Dudenhausen, J. W.,Grathwohl, D.,Haschke, F. (2008). Supplementation with 200 mg/day docosahexaenoic acid from mid-pregnancy through lactation improves the docosahexaenoic acid status of mothers with a habitually low fish intake and of their infants Ann Nutr Metab, 52(2), 157-66 | Intervention/exposure
226 | Bergstrand, O.,Hellers, G. (1983). Breast-feeding during infancy in patients who later develop Crohn’s disease Scand J Gastroenterol, 18(7), 903-6 | Outcome
227 | Bergstrom, A.,Skov, T. H.,Bahl, M. I.,Roager, H. M.,Christensen, L. B.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F.,Licht, T. R. (2014). Establishment of intestinal microbiota during early life: a longitudinal, explorative study of a large cohort of Danish infants Appl Environ Microbiol, 80(9), 2889-900 | Outcome
228 | Bergstrom, E.,Hernell, O.,Persson, L. A.,Vessby, B. (1995). Serum lipid values in adolescents are related to family history, infant feeding, and physical growth Atherosclerosis, 117(1), 1-13 | Intervention/exposure
229 | Beristain-Manterola, R.,Pasquetti-Ceccatelli, A.,Meléndez-Mier, G.,Sánchez-Escobar, O. A.,Cuevas-Covarrubias, S. A. (2010). Evaluation of iron status in healthy six-month-old infants in Mexican population: Evidence of a high prevalence of iron deficiency e-SPEN, 5(1), e37-e39 | Study design
230 | Berkowitz, C. D.,Uchiyama, N.,Tully, S. B.,Marble, R. D.,Spencer, M.,Stein, M. T.,Orr, D. P. (1985). Fever in infants less than two months of age: spectrum of disease and predictors of outcome Pediatr Emerg Care, 1(3), 128-35 | Study design, Participant health
231 | Berkowitz, R. J. (1985). Streptococcus mutans and dental caries in infants Compend Contin Educ Dent, 6(6), 463-6 | Study design
232 | Bernard, A.,Nickmilder, M. (2013). Association of breastfeeding with higher serum inhibin B level at adolescence JAMA Pediatr, 167(9), 869-70 | Study design, Outcome
233 | Bernard, J. Y.,Armand, M.,Garcia, C.,Forhan, A.,De Agostini, M.,Charles, M. A.,Heude, B. (2015). The association between linoleic acid levels in colostrum and child cognition at 2 and 3 y in the EDEN cohort Pediatr Res, 77(6), 829-35 | Outcome
234 | Bernard, J. Y.,De Agostini, M.,Forhan, A.,Alfaiate, T.,Bonet, M.,Champion, V.,Kaminski, M.,de Lauzon-Guillain, B.,Charles, M. A.,Heude, B. (2013). Breastfeeding duration and cognitive development at 2 and 3 years of age in the EDEN mother-child cohort J Pediatr, 163(1), 36-42 e1 | Outcome
235 | Bernard, J. Y.,De Agostini, M.,Forhan, A.,de Lauzon-Guillain, B.,Charles, M. A.,Heude, B. (2013). The dietary n6:n3 fatty acid ratio during pregnancy is inversely associated with child neurodevelopment in the EDEN mother-child cohort J Nutr, 143(9), 1481-8 | Outcome
236 | Bernardi, J. R.,Gama, C. M.,Vitolo, M. R. (2011). An infant feeding update program at healthcare centers and its impact on breastfeeding and morbidity Cadernos de Saude Publica, 27(6), 1213-1222 | Language
237 | Berseth, C. L.,Mitmesser, S. H.,Birch, E.,Khoury, J.,Bean, J.,Harris, C.,Scalabrin, D. (2011). Intake of DHA/ARA via breast milk or formula supplementation during infancy can affect the incidence and recurrence of allergic manifestations in young children Journal of Pediatric Gastroenterology and Nutrition. Conference: European Society for Paediatric Gastroenterology, Hepatology, and Nutrition Annual Meeting 2011 Sorrento Italy. Conference Start: 20110525 Conference End: 20110528. Conference Publication: (var.pagings), 52(Suppl 2), E61 | Publication status
238 | Betoko, A.,Charles, M. A.,Hankard, R.,Forhan, A.,Bonet, M.,Regnault, N.,Botton, J.,Saurel-Cubizolles, M. J.,de Lauzon-Guillain, B. (2014). Determinants of infant formula use and relation with growth in the first 4 months Matern Child Nutr, 10(2), 267-79 | Outcome
239 | Betran, A. P.,de Onis, M.,Lauer, J. A.,Villar, J. (2001). Ecological study of effect of breast feeding on infant mortality in Latin America Bmj, 323(7308), 303-6 | Study design
240 | Beyerlein, A.,Fahrmeir, L.,Mansmann, U.,Toschke, A. M. (2008). Alternative regression models to assess increase in childhood BMI BMC Med Res Methodol, 8(#issue#), 59 | Study design
241 | Bhan, M. K.,Arora, N. K.,Singh, K. D. (1991). Management of persistent diarrhea during infancy in clinical practice Indian J Pediatr, 58(6), 769-74 | Country, Study design
242 | Bhatia, B. D.,Banerjee, D.,Agarwal, D. K.,Agarwal, K. N. (1983). Exterogestate growth: relationship with maternal body size and dietary intakes Indian J Pediatr, 50(404), 241-6 | Country, Study design
243 | Bianchi, C.,Brambilla, P.,Cella, D.,Ragogna, F.,Tettamanti, C.,Del Puppo, M.,Kienle, M. G.,Chiumello, G.,Ruotolo, G. (1997). Influence of breast- and formula-feeding on plasma cholesterol precursor sterols throughout the first year of life J Pediatr, 131(6), 928-31 | Size of study groups
244 | Biering-Sorensen F,Hilden J,Biering-Sorensen K (1983). Breast-feeding and infant health in Copenhagen 1941-1972 Dan Med Bull, 30(#issue#), 36-41 | Study design, Outcome
245 | Biesbroek, G.,Bosch, A. A.,Wang, X.,Keijser, B. J.,Veenhoven, R. H.,Sanders, E. A.,Bogaert, D. (2014). The impact of breastfeeding on nasopharyngeal microbial communities in infants Am J Respir Crit Care Med, 190(3), 298-308 | Outcome
246 | Biesbroek, G.,Tsivtsivadze, E.,Sanders, E. A.,Montijn, R.,Veenhoven, R. H.,Keijser, B. J.,Bogaert, D. (2014). Early respiratory microbiota composition determines bacterial succession patterns and respiratory health in children Am J Respir Crit Care Med, 190(11), 1283-92 | Study design, Outcome
247 | Bilenko, N.,Fraser, D.,Naggan, L. (1999). Maternal knowledge and environmental factors associated with risk of diarrhea in Israeli Bedouin children Eur J Epidemiol, 15(10), 907-12 | Intervention/exposure
248 | Bilenko, N.,Ghosh, R.,Levy, A.,Deckelbaum, R. J.,Fraser, D. (2008). Partial breastfeeding protects Bedouin infants from infection and morbidity: prospective cohort study Asia Pac J Clin Nutr, 17(2), 243-9 | Outcome
249 | Bindon, J. R. (1985). The influence of infant feeding patterns on growth of children in American Samoa Med Anthropol, 9(2), 183-95 | Intervention/exposure
250 | Binns C,James J,Lee MK (2013). Trends in asthma, allergy and breastfeeding in Australia Breastfeed Rev, 21(#issue#), 7-8 | Study design
251 | Birch, E. E.,Carlson, S. E.,Hoffman, D. R.,Fitzgerald-Gustafson, K. M.,Fu, V. L.,Drover, J. R.,Castaneda, Y. S.,Minns, L.,Wheaton, D. K.,Mundy, D.,Marunycz, J.,Diersen-Schade, D. A. (2010). The DIAMOND (DHA Intake And Measurement Of Neural Development) Study: a double-masked, randomized controlled clinical trial of the maturation of infant visual acuity as a function of the dietary level of docosahexaenoic acid Am J Clin Nutr, 91(4), 848-59 | Intervention/exposure
252 | Birch, E. E.,Garfield, S.,Castaneda, Y.,Hughbanks-Wheaton, D.,Uauy, R.,Hoffman, D. (2007). Visual acuity and cognitive outcomes at 4 years of age in a double-blind, randomized trial of long-chain polyunsaturated fatty acid-supplemented infant formula Early Hum Dev, 83(5), 279-84 | Outcome
253 | Birch, E. E.,Hoffman, D. R.,Castaneda, Y. S.,Fawcett, S. L.,Birch, D. G.,Uauy, R. D. (2002). A randomized controlled trial of long-chain polyunsaturated fatty acid supplementation of formula in term infants after weaning at 6 wk of age Am J Clin Nutr, 75(3), 570-80 | Intervention/exposure
254 | Birch, E. E.,Hoffman, D. R.,Uauy, R.,Birch, D. G.,Prestidge, C. (1998). Visual acuity and the essentiality of docosahexaenoic acid and arachidonic acid in the diet of term infants Pediatr Res, 44(2), 201-9 | Size of study groups
255 | Birch, E.,Birch, D.,Hoffman, D.,Hale, L.,Everett, M.,Uauy, R. (1993). Breast-feeding and optimal visual development J Pediatr Ophthalmol Strabismus, 30(1), 33-8 | Size of study groups, Intervention/exposure
256 | Birkbeck JA,Scott HF (1980). 25-Hydroxycholecalciferol serum levels in breast-fed infants Arch Dis Child, 55(#issue#), 691-5 | Intervention/exposure
257 | Birkbeck, J. A.,Buckfield, P. M.,Silva, P. A. (1985). Lack of long-term effect of the method of infant feeding on growth Hum Nutr Clin Nutr, 39(1), 39-44 | Intervention/exposure
258 | Birkett, D. (2005). On bottle versus breast Health Serv J, 115(5957), 19 | Study design
259 | Bisgaard, H.,Halkjær, L. B.,Hinge, R.,Giwercman, C.,Palmer, C.,Silveira, L.,Strand, M. (2009). Risk analysis of early childhood eczema Journal of Allergy and Clinical Immunology, 123(6), 1355-1360.e5 | Intervention/exposure
260 | Bishara, S. E.,Nowak, A. J.,Kohout, F. J.,Heckert, D. A.,Hogan, M. M. (1987). Influence of feeding and non-nutritive sucking methods on the development of the dental arches: longitudinal study of the first 18 months of life Pediatr Dent, 9(1), 13-21 | Size of study groups, Intervention/exposure
261 | Bishara, S. E.,Warren, J. J.,Broffitt, B.,Levy, S. M. (2006). Changes in the prevalence of nonnutritive sucking patterns in the first 8 years of life Am J Orthod Dentofacial Orthop, 130(1), 31-6 | Intervention/exposure
262 | Bishop, W. S. (1985). Weaning the breast-fed toddler or preschooler Pediatr Nurs, 11(3), 211-4 | Study design
263 | Bjorke-Monsen, A. L. (2014). Is exclusive breastfeeding ensuring an optimal micronutrient status and psychomotor development in infants? Clin Biochem, 47(9), 714 | Study design
264 | Bjorksten, B.,Ait-Khaled, N.,Innes Asher, M.,Clayton, T. O.,Robertson, C. (2011). Global analysis of breast feeding and risk of symptoms of asthma, rhinoconjunctivitis and eczema in 6-7 year old children: ISAAC Phase Three Allergol Immunopathol (Madr), 39(6), 318-25 | Study design
265 | Blake, P. A.,Ramos, S.,MacDonald, K. L.,Rassi, V.,Gomes, T. A.,Ivey, C.,Bean, N. H.,Trabulsi, L. R. (1993). Pathogen-specific risk factors and protective factors for acute diarrheal disease in urban Brazilian infants J Infect Dis, 167(3), 627-32 | Participant health, Intervention/exposure
266 | Blattner, C. M.,Murase, J. E. (2014). A practice gap in pediatric dermatology: does breast-feeding prevent the development of infantile atopic dermatitis? J Am Acad Dermatol, 71(2), 405-6 | Study design
267 | Blom, L.,Dahlquist, G.,Nystrom, L.,Sandstrom, A.,Wall, S. (1989). The Swedish childhood diabetes study--social and perinatal determinants for diabetes in childhood Diabetologia, 32(1), 7-13 | Outcome
268 | Bloom, K.,Goldbloom, R. B.,Robinson, S. C.,Stevens, F. E. (1982). Breast versus formula feeding Acta Paediatr Scand Suppl, 300(#issue#), 1-26 | Study design, Outcome
269 | Bly, E.,Huntington, J.,Harper, A. L.,Vincent, E. C. (2013). What is the best age to start vitamin D supplementation to prevent rickets in breastfed newborns? Journal of Family Practice, 62(12), 755+763 | Study design
270 | Bocca, B.,Alimonti, A.,Giglio, L.,Di Pasquale, M.,Caroli, S.,Ambruzzi, M. A.,Bocca, A. P.,Coni, E. (2000). Nutritive significance of element speciation in breast milk. The case of calcium, copper, iron, magnesium, manganese, and zinc Adv Exp Med Biol, 478(#issue#), 385-6 | Study design, Outcome
271 | Boccolini, C. S.,Carvalho, M. L.,Oliveira, M. I.,Boccolini Pde, M. (2011). Breastfeeding can prevent hospitalization for pneumonia among children under 1 year old J Pediatr (Rio J), 87(5), 399-404 | Study design, Intervention/exposure
272 | Boccolini, C. S.,Carvalho, M. L.,Oliveira, M. I.,Perez-Escamilla, R. (2013). Breastfeeding during the first hour of life and neonatal mortality J Pediatr (Rio J), 89(2), 131-6 | Study design
273 | Bodington, M. J.,McNally, P. G.,Burden, A. C. (1994). Cow’s milk and type 1 childhood diabetes: no increase in risk Diabet Med, 11(7), 663-5 | Intervention/exposure
274 | Boediman, D.,Murakami, R.,Nakamura, H.,Matsuo, T. (1989). Plasma apolipoprotein and lipid profiles in infants in the first year of life Kobe J Med Sci, 35(3), 165-76 | Size of study groups
275 | Boerma, J. T.,Bicego, G. T. (1992). Preceding birth intervals and child survival: searching for pathways of influence Stud Fam Plann, 23(4), 243-56 | Study design, Intervention/exposure
276 | Bogen, D. L.,Hanusa, B. H.,Whitaker, R. C. (2004). The effect of breast-feeding with and without formula use on the risk of obesity at 4 years of age Obes Res, 12(9), 1527-35 | Outcome
277 | Bognetti, E.,Meschi, F.,Malavasi, C.,Pastore, M. R.,Sergi, A.,Illeni, M. T.,Maffeis, C.,Pinelli, L.,Chiumello, G. (1992). HLA-antigens in Italian type 1 diabetic patients: role of DR3/DR4 antigens and breast feeding in the onset of the disease Acta Diabetol, 28(3-4), 229-32 | Outcome
278 | Bohles, H.,Aschenbrenner, M.,Roth, M.,von Loewenich, V.,Ball, F.,Usadel, K. H. (1993). Development of thyroid gland volume during the first 3 months of life in breast-fed versus iodine-supplemented and iodine-free formula-fed infants Clin Investig, 71(1), 13-20 | Size of study groups
279 | Bolanos, A. V.,Caire, G.,Valencia, M. E.,Casanueva, E.,Roman Perez, R.,Calderon de la Barca, A. M. (2000). Energy intake and growth of breast-fed infants in two regions of Mexico Adv Exp Med Biol, 478(#issue#), 371-2 | Publication status
280 | Bond, S. (2008). Randomized trial provides strong evidence that prolonged, exclusive breastfeeding enhances cognitive development in children Journal of Midwifery & Women’s Health, 53(5), 472-473 2p | Study design
281 | Bonuck, K. A.,Freeman, K.,Trombley, M. (2006). Randomized controlled trial of a prenatal and postnatal lactation consultant intervention on infant health care use Arch Pediatr Adolesc Med, 160(9), 953-60 | Outcome
282 | Bonuck, K.,Avraham, S. B.,Lo, Y.,Kahn, R.,Hyden, C. (2014). Bottle-weaning intervention and toddler overweight J Pediatr, 164(2), 306-12 e1-2 | Intervention/exposure, Outcome
283 | Boonyaratavej, N.,Suriyawongpaisal, P.,Takkinsatien, A.,Wanvarie, S.,Rajatanavin, R.,Apiyasawat, P. (2001). Physical activity and risk factors for hip fractures in Thai women Osteoporos Int, 12(3), 244-8 | Participant age, Intervention/exposure
284 | Borch-Johnsen K,Joner G,Mandrup-Poulsen T,Christy M,Zachau-Christiansen B,Kastrup K,Nerup J (1984). Relation between breast-feeding and incidence rates of insulin-dependent diabetes mellitus. A hypothesis Lancet, 2(#issue#), 1083-6 | Outcome
285 | Bordeaux, D. R.,Heidenreich, J. G.,Schlagheck, D. J.,Crabtree, J. T.,Trachtenbarg, D. E. (1982). Infant nutrition J Fam Pract, 14(1), 145-50 | Study design
286 | Borgnolo, G.,Barbone, F.,Scornavacca, G.,Franco, D.,Vinci, A.,Iuculano, F. (1996). A case-control study of Salmonella gastrointestinal infection in Italian children Acta Paediatr, 85(7), 804-8 | Participant health
287 | Bornhorst, C.,Siani, A.,Russo, P.,Kourides, Y.,Sion, I.,Molnar, D.,Moreno, L. A.,Rodriguez, G.,Ben-Shlomo, Y.,Howe, L.,Lissner, L.,Mehlig, K.,Regber, S.,Bammann, K.,Foraita, R.,Ahrens, W.,Tilling, K. (2016). Early Life Factors and Inter-Country Heterogeneity in BMI Growth Trajectories of European Children: The IDEFICS Study PLoS One, 11(2), e0149268 | Outcome
288 | Bortolini, G. A.,Vitolo, M. R. (2012). The impact of systematic dietary counseling during the first year of life on prevalence rates of anemia and iron deficiency at 12-16 months J Pediatr (Rio J), 88(1), 33-9 | Intervention/exposure
289 | Boshuizen, H. C.,Verkerk, P. H.,Reerink, J. D.,Herngreen, W. P.,Zaadstra, B. M.,Verloove-Vanhorick, S. P. (1998). Maternal smoking during lactation: relation to growth during the first year of life in a Dutch birth cohort Am J Epidemiol, 147(2), 117-26 | Intervention/exposure
290 | Boskabadi, H.,Ramazanzadeh, M.,Zakerihamidi, M.,Omran, F. R. (2014). Risk factors of breast problems in mothers and its effects on newborns Iranian Red Crescent Medical Journal, 16(6), #Pages# | Intervention/exposure, Outcome
291 | Boulton, J. (1981). Nutrition in childhood and its relationships to early somatic growth, body fat, blood pressure, and physical fitness Acta Paediatr Scand Suppl, 284(#issue#), 1-85 | Publication status
292 | Boutwell, B. B.,Beaver, K. M.,Barnes, J. C. (2012). Role of breastfeeding in childhood cognitive development: a propensity score matching analysis J Paediatr Child Health, 48(9), 840-5 | Outcome
293 | Bouwstra, H.,Boersma, E. R.,Boehm, G.,Dijck-Brouwer, D. A.,Muskiet, F. A.,Hadders-Algra, M. (2003). Exclusive breastfeeding of healthy term infants for at least 6 weeks improves neurological condition J Nutr, 133(12), 4243-5 | Outcome
294 | Bouwstra, H.,Dijck-Brouwer, D. A.,Boehm, G.,Boersma, E. R.,Muskiet, F. A.,Hadders-Algra, M. (2005). Long-chain polyunsaturated fatty acids and neurological developmental outcome at 18 months in healthy term infants Acta Paediatr, 94(1), 26-32 | Outcome
295 | Bouwstra, H.,Dijck-Brouwer, D. A.,Wildeman, J. A.,Tjoonk, H. M.,van der Heide, J. C.,Boersma, E. R.,Muskiet, F. A.,Hadders-Algra, M. (2003). Long-chain polyunsaturated fatty acids have a positive effect on the quality of general movements of healthy term infants Am J Clin Nutr, 78(2), 313-8 | Intervention/exposure
296 | Bouwstra, H.,Dijck-Brouwer, J.,Decsi, T.,Boehm, G.,Boersma, E. R.,Muskiet, F. A.,Hadders-Algra, M. (2006). Neurologic condition of healthy term infants at 18 months: positive association with venous umbilical DHA status and negative association with umbilical trans-fatty acids Pediatr Res, 60(3), 334-9 | Intervention/exposure
297 | Bove, I.,Campoy, C.,Uauy, R.,Miranda, T.,Cerruti, F. (2014). Trends in early growth indices in the first 24 months of life in Uruguay over the past decade J Health Popul Nutr, 32(4), 600-7 | Study design
298 | Bramhagen, A. C.,Svahn, J.,Hallstrom, I.,Axelsson, I. (2011). Factors influencing iron nutrition among one-year-old healthy children in Sweden J Clin Nurs, 20(13-14), 1887-94 | Study design
299 | Brams, M.,Maloney, J. (1983). “Nursing bottle caries” in breast-fed children J Pediatr, 103(3), 415-6 | Study design
300 | Brandenburg, A. H.,Jeannet, P. Y.,Steensel-Moll, H. A.,Ott, A.,Rothbarth, P. H.,Wunderli, W.,Suter, S.,Neijens, H. J.,Osterhaus, A. D.,Siegrist, C. A. (1997). Local variability in respiratory syncytial virus disease severity Arch Dis Child, 77(5), 410-4 | Study design, Participant health
301 | Brandstrom, A.,Brostrom, G.,Persson, L. A. (1984). The impact of feeding patterns on infant mortality in a nineteenth century Swedish parish J Trop Pediatr, 30(3), 154-9 | Study design, Intervention/exposure
302 | Bray, K. K.,Branson, B. G.,Williams, K. (2003). Early childhood caries in an urban health department: an exploratory study J Dent Hyg, 77(4), 225-32 | Study design
303 | Brew, B. K.,Kull, I.,Garden, F.,Almqvist, C.,Bergstrom, A.,Lind, T.,Webb, K.,Wickman, M.,Marks, G. B. (2012). Breastfeeding, asthma, and allergy: a tale of two cities Pediatr Allergy Immunol, 23(1), 75-82 | Study design, Redundant data with another study
304 | Brew, B. K.,Marks, G. B.,Almqvist, C.,Cistulli, P. A.,Webb, K.,Marshall, N. S. (2014). Breastfeeding and snoring: a birth cohort study PLoS One, 9(1), e84956 | Outcome
305 | Briggs, D. (1992). Baby milks and the EC. Infant nutrition Nurs Times, 88(32), 24-6 | Study design
306 | Brion, M. J. A.,Lawlor, D. A.,Matijasevich, A.,Horta, B.,Anselmi, L.,Araújo, C. L.,Menezes, A. M. B.,Victora, C. G.,Smith, G. D. (2011). What are the causal effects of breastfeeding on IQ, obesity and blood pressure? Evidence from comparing high-income with middle-income cohorts International Journal of Epidemiology, 40(3), 670-680 | Intervention/exposure
307 | Broad, F. E.,Duganzich, D. M. (1983). The effects of infant feeding, birth order, occupation and socio-economic status on speech in six-year-old children N Z Med J, 96(734), 483-6 | Intervention/exposure
308 | Brodish, M. S. (1982). Relationship of early bonding to initial infant feeding patterns in bottle-fed newborns JOGN Nurs, 11(4), 248-52 | Intervention/exposure
309 | Brooke OG (1983). Supplementary vitamin D in infancy and childhood Arch Dis Child, 58(#issue#), 573-4 | Study design
310 | Brooks, J. G.,Gilbert, R. E.,Flemming, P. J.,Berry, P. J.,Golding, J. (1994). Postnatal growth preceding sudden infant death syndrome Pediatrics, 94(4 Pt 1), 456-61 | Outcome
311 | Broor, S.,Pandey, R. M.,Ghosh, M.,Maitreyi, R. S.,Lodha, R.,Singhal, T.,Kabra, S. K. (2001). Risk factors for severe acute lower respiratory tract infection in under-five children Indian Pediatr, 38(12), 1361-9 | Country
312 | Brown, A.,Lee, M. (2012). Breastfeeding during the first year promotes satiety responsiveness in children aged 18-24 months Pediatr Obes, 7(5), 382-90 | Outcome
313 | Brown, C. M.,Austin, D. W.,Busija, L. (2014). Observable essential fatty acid deficiency markers and autism spectrum disorder Breastfeed Rev, 22(2), 21-6 | Study design, Size of study groups
314 | Brown, J. P.,Junner, C.,Liew, V. (1985). A study of Streptococcus mutans levels in both infants with bottle caries and their mothers Aust Dent J, 30(2), 96-8 | Intervention/exposure
315 | Brown, K. H.,Black, R. E.,Lopez de Romana, G.,Creed de Kanashiro, H. (1989). Infant-feeding practices and their relationship with diarrheal and other diseases in Huascar (Lima), Peru Pediatrics, 83(1), 31-40 | Intervention/exposure
316 | Brown, K. H.,Stallings, R. Y.,de Kanashiro, H. C.,Lopez de Romana, G.,Black, R. E. (1990). Effects of common illnesses on infants’ energy intakes from breast milk and other foods during longitudinal community-based studies in Huascar (Lima), Peru Am J Clin Nutr, 52(6), 1005-13 | Outcome
317 | Broxton, D. (2008). Infant feeding research summaries International Journal of Childbirth Education, 23(2), 28-31 4p | Country
318 | Bruce, L.,Lieberman, L. S. (1987). Nutritional anthropometry and dietary intake of children from the Las Cuevas region of the Dominican Republic Arch Latinoam Nutr, 37(2), 250-8 | Study design
319 | Bruerd, B.,Kinney, M. B.,Bothwell, E. (1989). Preventing baby bottle tooth decay in American Indian and Alaska native communities: a model for planning Public Health Rep, 104(6), 631-40 | Intervention/exposure
320 | Bruno, G.,Milita, O.,Ferrara, M.,Nisini, R.,Cantani, A.,Businco, L. (1993). Prevention of atopic diseases in high risk babies (long-term follow-up) Allergy Proc, 14(3), 181-6; discussion 186-7 | Intervention/exposure
321 | Brunser, O.,Espinoza, J.,Figueroa, G.,Araya, M.,Spencer, E.,Hilpert, H.,Link-Amster, H.,Brussow, H. (1992). Field trial of an infant formula containing anti-rotavirus and anti-Escherichia coli milk antibodies from hyperimmunized cows J Pediatr Gastroenterol Nutr, 15(1), 63-72 | Intervention/exposure
322 | Buckley, K. M. (2001). Long-term breastfeeding: nourishment or nurturance? J Hum Lact, 17(4), 304-12 | Study design, Intervention/exposure
323 | Buinauskiene, J.,Baliutaviciene, D.,Zalinkevicius, R. (2004). Glucose tolerance of 2- to 5-yr-old offspring of diabetic mothers Pediatric Diabetes, 5(3), 143-146 | Intervention/exposure
324 | Bulk-Bunschoten, A. M.,Pasker-de Jong, P. C.,van Wouwe, J. P.,de Groot, C. J. (2008). Ethnic variation in infant-feeding practices in the Netherlands and weight gain at 4 months J Hum Lact, 24(1), 42-9 | Intervention/exposure, Outcome
325 | Bulk-Bunschoten, A. M.,van Bodegom, S.,Reerink, J. D.,de Jong, P. C.,de Groot, C. J. (2002). Weight and weight gain at 4 months (The Netherlands 1998): influences of nutritional practices, socio-economic and ethnic factors Paediatr Perinat Epidemiol, 16(4), 361-9 | Intervention/exposure
326 | Bulkow, L. R.,Singleton, R. J.,DeByle, C.,Miernyk, K.,Redding, G.,Hummel, K. B.,Chikoyak, L.,Hennessy, T. W. (2012). Risk factors for hospitalization with lower respiratory tract infections in children in rural Alaska Pediatrics, 129(5), e1220-7 | Outcome
327 | Bulkow, L. R.,Singleton, R. J.,Karron, R. A.,Harrison, L. H. (2002). Risk factors for severe respiratory syncytial virus infection among Alaska native children Pediatrics, 109(2), 210-6 | Outcome
328 | Bunik, M.,Shobe, P.,O’Connor, M. E.,Beaty, B.,Langendoerfer, S.,Crane, L. (2007). Randomized controlled trial to evaluate a telephone support intervention for breastfeeding in low-income Latina mothers Breastfeeding medicine, 2(3), 183 | Study design
329 | Burd, L.,Fisher, W.,Kerbeshian, J.,Vesely, B.,Durgin, B.,Reep, P. (1988). A comparison of breastfeeding rates among children with pervasive developmental disorder, and controls J Dev Behav Pediatr, 9(5), 247-51 | Study design
330 | Burdette, H. L.,Whitaker, R. C. (2007). Differences by race and ethnicity in the relationship between breastfeeding and obesity in preschool children Ethn Dis, 17(3), 467-70 | Outcome
331 | Burdette, H. L.,Whitaker, R. C.,Hall, W. C.,Daniels, S. R. (2006). Breastfeeding, introduction of complementary foods, and adiposity at 5 y of age Am J Clin Nutr, 83(3), 550-8 | Outcome
332 | Burgess, S. W.,Dakin, C. J.,O’Callaghan, M. J. (2006). Breastfeeding does not increase the risk of asthma at 14 years Pediatrics, 117(4), e787-92 | Outcome
333 | Burke, V.,Beilin, L. J.,Simmer, K.,Oddy, W. H.,Blake, K. V.,Doherty, D.,Kendall, G. E.,Newnham, J. P.,Landau, L. I.,Stanley, F. J. (2005). Breastfeeding and overweight: longitudinal analysis in an Australian birth cohort J Pediatr, 147(1), 56-61 | Outcome
334 | Burns, E.,Schmied, V.,Sheehan, A.,Fenwick, J. (2009). Let women express themselves - breastfeeding study Australian Nursing Journal, 17(2), 44-45 2p | Study design
335 | Burr, M. L.,Limb, E. S.,Maguire, M. J.,Amarah, L.,Eldridge, B. A.,Layzell, J. C.,Merrett, T. G. (1993). Infant feeding, wheezing, and allergy: a prospective study Arch Dis Child, 68(6), 724-8 | Outcome
336 | Burr, M. L.,Miskelly, F. G.,Butland, B. K.,Merrett, T. G.,Vaughan-Williams, E. (1989). Environmental factors and symptoms in infants at high risk of allergy J Epidemiol Community Health, 43(2), 125-32 | Outcome
337 | Businco, L.,Marchetti, F.,Pellegrini, G.,Cantani, A.,Perlini, R. (1983). Prevention of atopic disease in “at-risk newborns” by prolonged breast-feeding Ann Allergy, 51(2 Pt 2), 296-9 | Intervention/exposure
338 | Butland, B. K.,Strachan, D. P.,Lewis, S.,Bynner, J.,Butler, N.,Britton, J. (1997). Investigation into the increase in hay fever and eczema at age 16 observed between the 1958 and 1970 British birth cohorts BMJ, 315(7110), 717-21 | Intervention/exposure
339 | Butte, N. F. (2009). Impact of infant feeding practices on childhood obesity Journal of Nutrition, 139(2), 412S-416S | Study design
340 | Butte, N. F.,Smith, E. O.,Garza, C. (1990). Energy utilization of breast-fed and formula-fed infants Am J Clin Nutr, 51(3), 350-8 | Size of study groups, Intervention/exposure
341 | Butte, N. F.,Wong, W. W.,Ferlic, L.,Smith, E. O.,Klein, P. D.,Garza, C. (1990). Energy expenditure and deposition of breast-fed and formula-fed infants during early infancy Pediatr Res, 28(6), 631-40 | Study design, Size of study groups
342 | Butte, N. F.,Wong, W. W.,Hopkinson, J. M.,Smith, E. O.,Ellis, K. J. (2000). Infant feeding mode affects early growth and body composition Pediatrics, 106(6), 1355-66 | Size of study groups
343 | Butters, L.,McCabe, R. (1988). The influence of breast and bottle feeding on blood pressure Midwifery, 4(3), 130-2 | Study design, Outcome
344 | Buyken, A. E.,Karaolis-Danckert, N.,Remer, T.,Bolzenius, K.,Landsberg, B.,Kroke, A. (2008). Effects of breastfeeding on trajectories of body fat and BMI throughout childhood Obesity (Silver Spring), 16(2), 389-95 | Intervention/exposure
345 | Bystrova, K.,Matthiesen, A. S.,Widstrom, A. M.,Ransjo-Arvidson, A. B.,Welles-Nystrom, B.,Vorontsov, I.,Uvnas-Moberg, K. (2007). The effect of Russian Maternity Home routines on breastfeeding and neonatal weight loss with special reference to swaddling Early Hum Dev, 83(1), 29-39 | Study design, Intervention/exposure
346 | Cable, N.,Bartley, M.,McMunn, A.,Kelly, Y. (2010). 011 Gender differences in the effect of breast feeding on adult psychological well-being Journal of Epidemiology & Community Health, 64(#issue#), A4-5 1p | Publication status
347 | Cable, N.,Bartley, M.,McMunn, A.,Kelly, Y. (2012). Gender differences in the effect of breastfeeding on adult psychological well-being Eur J Public Health, 22(5), 653-8 | Outcome
348 | Cai, S.,Pang, W. W.,Low, Y. L.,Sim, L. W.,Sam, S. C.,Bruntraeger, M. B.,Wong, E. Q.,Fok, D.,Broekman, B. F.,Singh, L.,Richmond, J.,Agarwal, P.,Qiu, A.,Saw, S. M.,Yap, F.,Godfrey, K. M.,Gluckman, P. D.,Chong, Y. S.,Meaney, M. J.,Kramer, M. S.,Rifkin-Graboi, A. (2015). Infant feeding effects on early neurocognitive development in Asian children Am J Clin Nutr, 101(2), 326-36 | Outcome
349 | Calamaro, C. J. (2000). Infant nutrition in the first year of life: tradition or science? Pediatr Nurs, 26(2), 211-5 | Study design
350 | Calvo, E. B.,Galindo, A. C.,Aspres, N. B. (1992). Iron status in exclusively breast-fed infants Pediatrics, 90(3 I), 375-379 | Size of study groups
351 | Cama, R. I.,Parashar, U. D.,Taylor, D. N.,Hickey, T.,Figueroa, D.,Ortega, Y. R.,Romero, S.,Perez, J.,Sterling, C. R.,Gentsch, J. R.,Gilman, R. H.,Glass, R. I. (1999). Enteropathogens and other factors associated with severe disease in children with acute watery diarrhea in Lima, Peru Journal of Infectious Diseases, 179(5), 1139-1144 | Participant health
352 | Camara, A. A.,Silva, J. M.,Ferriani, V. P.,Tobias, K. R.,Macedo, I. S.,Padovani, M. A.,Harsi, C. M.,Cardoso, M. R.,Chapman, M. D.,Arruda, E.,Platts-Mills, T. A.,Arruda, L. K. (2004). Risk factors for wheezing in a subtropical environment: role of respiratory viruses and allergen sensitization J Allergy Clin Immunol, 113(3), 551-7 | Outcome
353 | Camargo-Figuera, F. A.,Barros, A. J.,Santos, I. S.,Matijasevich, A.,Barros, F. C. (2014). Early life determinants of low IQ at age 6 in children from the 2004 Pelotas Birth Cohort: a predictive approach BMC Pediatr, 14(#issue#), 308 | Outcome
354 | Cameron M,Hofvander Y (1984). Problems associated with breast-milk substitutes Nurs J India, 75(#issue#), 245-6, 247, 249-50 | Study design
355 | Cameron, S. L.,Gray, A. R.,Taylor, R. W.,Lawrence, J. A.,Galland, B. C.,Hanna, M. B.,Heath, A. L. M.,Sayers, R. M.,Taylor, B. J. (2014). Excessive growth from 6 to 24 months of age: Results from the prevention of overweight in infancy (POI) randomised controlled trial Archives of disease in childhood, 99(#issue#), A109 | Publication status
356 | Campbell N (1981). The nutritional and immunological benefits of breast milk Aust Nurses J, 10(#issue#), 40-3, 47 | Study design
357 | Campos-Martinez, A.,Serrano- Lopez, L.,Medina- Navarro, M.,Ochoa- Herrera, J.,Pena-Caballero, M. (2012). Levels of docosahexaenoic acid in pregnant women and their children after taking a fish oil enriched diet Journal of maternal-fetal & neonatal medicine, 25(#issue#), 92 | Publication status
358 | Campus, G.,Solinas, G.,Sanna, A.,Maida, C.,Castiglia, P. (2007). Determinants of ECC in Sardinian preschool children Community Dent Health, 24(4), 253-6 | Intervention/exposure
359 | Camurdan, M. O.,Camurdan, A. D.,Polat, S.,Beyazova, U. (2011). Growth patterns of large, small, and appropriate for gestational age infants: impacts of long-term breastfeeding: a retrospective cohort study J Pediatr Endocrinol Metab, 24(7-8), 463-8 | Intervention/exposure
360 | Cant, A. J.,Bailes, J. A. (1984). How should we feed the potentially allergic infant? Hum Nutr Appl Nutr, 38(6), 474-6 | Study design
361 | Cantani, A.,Micera, M. (2005). Neonatal cow milk sensitization in 143 case-reports: role of early exposure to cow’s milk formula Eur Rev Med Pharmacol Sci, 9(4), 227-30 | Study design, Participant health
362 | Cantey, J. B.,Bascik, S. L.,Heyne, N. G.,Gonzalez, J. R.,Jackson, G. L.,Rogers, V. L.,Sheffield, J. S.,Trevino, S.,Sendelbach, D.,Wendel, G. D.,Sanchez, P. J. (2013). Prevention of mother-to-infant transmission of influenza during the postpartum period Am J Perinatol, 30(3), 233-40 | Study design, Intervention/exposure
363 | Capeding, R.,Gepanayao, C. P.,Calimon, N.,Lebumfacil, J.,Davis, A. M.,Stouffer, N.,Harris, B. J. (2010). Lutein-fortified infant formula fed to healthy term infants: evaluation of growth effects and safety Nutr J, 9(#issue#), 22 | Intervention/exposure
364 | Caplan, L. S.,Erwin, K.,Lense, E.,Hicks, J., Jr. (2008). The potential role of breast-feeding and other factors in helping to reduce early childhood caries J Public Health Dent, 68(4), 238-41 | Study design, Intervention/exposure
365 | Capozzi, L.,Russo, R.,Bertocco, F.,Ferrara, D.,Ferrara, M. (2010). Diet and iron deficiency in the first year of life: a retrospective study Hematology, 15(6), 410-3 | Participant health
366 | Capozzi, L.,Russo, R.,Bertocco, F.,Ferrara, D.,Ferrara, M. (2011). Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits Hematology, 16(5), 261-4 | Intervention/exposure
367 | Carberry, A. E.,Colditz, P. B.,Lingwood, B. E. (2010). Body composition from birth to 4.5 months in infants born to non-obese women Pediatr Res, 68(1), 84-8 | Size of study groups
368 | Carling, S. J.,Demment, M. M.,Kjolhede, C. L.,Olson, C. M. (2015). Breastfeeding duration and weight gain trajectory in infancy Pediatrics, 135(1), 111-9 | Outcome
369 | Carlsen, K. H.,Larsen, S.,Bjerve, O.,Leegaard, J. (1987). Acute bronchiolitis: predisposing factors and characterization of infants at risk Pediatr Pulmonol, 3(3), 153-60 | Size of study groups
370 | Carlson, S. E.,DeVoe, P. W.,Barness, L. A. (1982). Effect of infant diets with different polyunsaturated to saturated fat ratios on circulating high-density lipoproteins J Pediatr Gastroenterol Nutr, 1(3), 303-9 | Size of study groups
371 | Carlson, S. E.,Ford, A. J.,Werkman, S. H.,Peeples, J. M.,Koo, W. W. (1996). Visual acuity and fatty acid status of term infants fed human milk and formulas with and without docosahexaenoate and arachidonate from egg yolk lecithin Pediatr Res, 39(5), 882-8 | Outcome
372 | Carpenter, R.,McGarvey, C.,Mitchell, E. A.,Tappin, D. M.,Vennemann, M. M.,Smuk, M.,Carpenter, J. R. (2013). Bed sharing when parents do not smoke: Is there a risk of SIDS? An individual level analysis of five major case-control studies BMJ Open, 3(5), #Pages# | Outcome
373 | Carr, A. (2009). Breastfeeding and the WIC program Breastfeed Med, 4 Suppl 1(#issue#), S57-8 | Study design
374 | Carrascoza, K. C.,Possobon Rde, F.,Tomita, L. M.,Moraes, A. B. (2006). Consequences of bottle-feeding to the oral facial development of initially breastfed children J Pediatr (Rio J), 82(5), 395-7 | Language
375 | Carroll, T. P. (1994). Substantially increasing breastfeeding: an accomplishment of the Alabama WIC Program J Hum Lact, 10(2), 129-30 | Study design, Outcome
376 | Carson, C. G. (2013). Risk factors for developing atopic dermatitis Dan Med J, 60(7), B4687 | Intervention/exposure
377 | Carter, C. S.,Porges, E. C. (2011). Parenthood, stress, and the brain Biol Psychiatry, 70(9), 804-5 | Study design
378 | Carvalho, R.,Johnson, E.,Kozlosky, M.,Scheimann, A. O. (2008). Clinical profile of the overweight child in the new millennium Clin Pediatr (Phila), 47(5), 476-82 | Study design, Participant health
379 | Casazza, Krista,Fernandez, Jose R.,Allison, David B. (2012). Modest Protective Effects of Breast-feeding on Obesity: Is the Evidence Truly Supportive? Nutrition Today, 47(1), 33-40 8p | Study design
380 | Casiday, R. E.,Wright, C. M.,Panter-Brick, C.,Parkinson, K. N. (2004). Do early infant feeding patterns relate to breast-feeding continuation and weight gain? Data from a longitudinal cohort study Eur J Clin Nutr, 58(9), 1290-6 | Outcome
381 | Caspi, A.,Williams, B.,Kim-Cohen, J.,Craig, I. W.,Milne, B. J.,Poulton, R.,Schalkwyk, L. C.,Taylor, A.,Werts, H.,Moffitt, T. E. (2007). Moderation of breastfeeding effects on the IQ by genetic variation in fatty acid metabolism Proc Natl Acad Sci U S A, 104(47), 18860-5 | Outcome
382 | Cassimos, D. C.,Tsalkidis, A.,Tripsianis, G. A.,Stogiannidou, A.,Anthracopoulos, M.,Ktenidou-Kartali, S.,Aivazis, V.,Gardikis, S.,Chatzimichael, A. (2008). Asthma, lung function and sensitization in school children with a history of bronchiolitis Pediatr Int, 50(1), 51-6 | Study design
383 | Castelo, P. M.,Gaviao, M. B.,Pereira, L. J.,Bonjardim, L. R. (2010). Maximal bite force, facial morphology and sucking habits in young children with functional posterior crossbite J Appl Oral Sci, 18(2), 143-8 | Study design, Size of study groups
384 | Castiglione, F.,Diaferia, M.,Morace, F.,Labianca, O.,Meucci, C.,Cuomo, A.,Panarese, A.,Romano, M.,Sorrentini, I.,D’Onofrio, C.,Caporaso, N.,Rispo, A. (2012). Risk factors for inflammatory bowel diseases according to the “hygiene hypothesis”: a case-control, multi-centre, prospective study in Southern Italy J Crohns Colitis, 6(3), 324-9 | Outcome
385 | Castillo, C.,Atalah, E.,Riumallo, J.,Castro, R. (1996). Breast-feeding and the nutritional status of nursing children in Chile Bull Pan Am Health Organ, 30(2), 125-33 | Study design
386 | Castro-Rodriguez, J. A.,Mallol, J.,Rodriguez, J.,Auger, F.,Andrade, R. (2008). Risk factors for X-ray pneumonia in the first year of life and its relation to wheezing: a longitudinal study in a socioeconomic disadvantaged population Allergol Immunopathol (Madr), 36(1), 3-8 | Outcome
387 | Castro-Rodriguez, J. A.,Stern, D. A.,Halonen, M.,Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D. (2001). Relation between infantile colic and asthma/atopy: a prospective study in an unselected population Pediatrics, 108(4), 878-82 | Outcome
388 | Cattaneo, A. (2013). Infant and young child feeding: solid facts Breastfeed Rev, 21(2), 7-9 | Study design
389 | Cattaneo, A.,Ronfani, L.,Burmaz, T.,Quintero-Romero, S.,Macaluso, A.,Di Mario, S. (2006). Infant feeding and cost of health care: a cohort study Acta Paediatr, 95(5), 540-6 | Outcome
390 | Cattaneo, A.,Timmer, A.,Bomestar, T.,Bua, J.,Kumar, S.,Tamburlini, G. (2008). Child nutrition in countries of the Commonwealth of Independent States: time to redirect strategies? Public Health Nutr, 11(12), 1209-19 | Study design
391 | Caudri, D.,Savenije, O. E.,Smit, H. A.,Postma, D. S.,Koppelman, G. H.,Wijga, A. H.,Kerkhof, M.,Gehring, U.,Hoekstra, M. O.,Brunekreef, B.,de Jongste, J. C. (2013). Perinatal risk factors for wheezing phenotypes in the first 8 years of life Clin Exp Allergy, 43(12), 1395-405 | Outcome
392 | Caulfield, L. E.,Bentley, M. E.,Ahmed, S. (1996). Is prolonged breastfeeding associated with malnutrition? Evidence from nineteen demographic and health surveys Int J Epidemiol, 25(4), 693-703 | Study design
393 | Caulfield, L. E.,Bose, A.,Chandyo, R. K.,Nesamvuni, C.,de Moraes, M. L.,Turab, A.,Patil, C.,Mahfuz, M.,Ambikapathi, R.,Ahmed, T. (2014). Infant feeding practices, dietary adequacy, and micronutrient status measures in the MAL-ED study Clin Infect Dis, 59 Suppl 4(#issue#), S248-54 | Study design
394 | Cavalcante e Silva, A.,Correia, L. L.,Campos, J. S.,Andrade, F. M.,Silveira, D. M.,Leite, A. J.,Rocha, H. A.,Machado, M. M.,Cunha, A. J. (2015). Reducing child mortality: the contribution of Ceara state, northeast of Brazil, on achieving the Millennium Development Goal 4 in Brazil Matern Child Health J, 19(4), 700-6 | Study design
395 | Çelikkiran, S.,Bozkurt, H.,Coşkun, M. (2015). Denver developmental test findings and their relationship with sociodemographic variables in a large community sample of 0–4-year-old children Noropsikiyatri Arsivi, 52(2), 180-184 | Study design
396 | Celikkiran, S.,Bozkurt, H.,Coskun, M. (2015). Denver developmental test findings and their relationship with sociodemographic variables in a large community sample of 0-4-year-old children Noropsikiyatri Arsivi, 52(2), 180-4 | Study design
397 | Cerrato, P. L. (1992). Preventing food allergies Rn, 55(10), 73-5 | Study design
398 | Cerrato, P. L. (1993). Does milk cause juvenile diabetes? Rn, 56(1), 69-72 | Study design
399 | Cesar, J. A.,Victora, C. G.,Barros, F. C.,Santos, I. S.,Flores, J. A. (1999). Impact of breast feeding on admission for pneumonia during postneonatal period in Brazil: nested case-control study BMJ, 318(7194), 1316-20 | Intervention/exposure
400 | Chaffee, B. W.,Feldens, C. A.,Vitolo, M. R. (2014). Association of long-duration breastfeeding and dental caries estimated with marginal structural models Ann Epidemiol, 24(6), 448-54 | Outcome
401 | Chaimay, B.,Ruagdaraganon, N.,Thinkhamrop, B.,Thinkhamrop, J. (2015). Association between infant feeding practices and first meaningful words at first year of life: a prospective cohort study of Thai children Asia Pac J Public Health, 27(2), NP1071-84 | Outcome
402 | Challacombe, D. N.,Mecrow, I. K.,Elliott, K.,Clarke, F. J.,Wheeler, E. E. (1997). Changing infant feeding practices and declining incidence of coeliac disease in West Somerset Arch Dis Child, 77(3), 206-9 | Size of study groups, Outcome
403 | Chaman, R.,Alami, A.,Emamian, M. H.,Naieni, K. H.,Mirmohammadkhani, M.,Ahmadnezhad, E.,Entezarmahdi, R.,Shati, M.,Shariati, M. (2012). Important risk factors of mortality among children aged 1-59 months in rural areas of Shahroud, Iran: A community-based nested case-control study International Journal of Preventive Medicine, 3(12), 875-879 | Outcome
404 | Chan, G. M.,Leeper, L.,Book, L. S. (1987). Effects of soy formulas on mineral metabolism in term infants Am J Dis Child, 141(5), 527-30 | Size of study groups
405 | Chan, G. M.,Roberts, C. C.,Folland, D.,Jackson, R. (1982). Growth and bone mineralization of normal breast-fed infants and the effects of lactation on maternal bone mineral status Am J Clin Nutr, 36(3), 438-43 | Size of study groups
406 | Chandra J,Jain V,Narayan S,Sharma S,Singh V,Kapoor AK,Batra S (2002). Folate and cobalamin deficiency in megaloblastic anemia in children Indian Pediatr, 39(#issue#), 453-7 | Country
407 | Chandra, R. K. (1997). Five-year follow-up of high-risk infants with family history of allergy who were exclusively breast-fed or fed partial whey hydrolysate, soy, and conventional cow’s milk formulas J Pediatr Gastroenterol Nutr, 24(4), 380-8 | Retracted
408 | Chandra, R. K.,Hamed, A. (1991). Cumulative incidence of atopic disorders in high risk infants fed whey hydrolysate, soy, and conventional cow milk formulas Ann Allergy, 67(2 Pt 1), 129-32 | Intervention/exposure
409 | Chandra, R. K.,Puri, S.,Cheema, P. S. (1985). Predictive value of cord blood IgE in the development of atopic disease and role of breast-feeding in its prevention Clin Allergy, 15(6), 517-22 | Intervention/exposure
410 | Chandra, R. K.,Puri, S.,Hamed, A. (1989). Influence of maternal diet during lactation and use of formula feeds on development of atopic eczema in high risk infants BMJ 1989 Oct 7;299(6704):896 BMJ (Clinical research ed.), 299(6693), 228-30 | Retracted
411 | Chandra, R. K.,Puri, S.,Suraiya, C.,Cheema, P. S. (1986). Influence of maternal food antigen avoidance during pregnancy and lactation on incidence of atopic eczema in infants Clin Allergy, 16(6), 563-9 | Reliability of the data is questionable (other articles by the author retracted)
412 | Chandran, L.,Gelfer, P. (2006). Breastfeeding: the essential principles Pediatr Rev, 27(11), 409-17 | Study design
413 | Chang YT,Germain-Lee EL,Doran TF,Migeon CJ,Levine MA,Berkovitz GD (1992). Hypocalcemia in nonwhite breast-fed infants. Vitamin D deficiency revisited Clin Pediatr (Phila), 31(#issue#), 695-8 | Study design
414 | Chanoine, J. P.,Boulvain, M.,Bourdoux, P.,Pardou, A.,Van Thi, H. V.,Ermans, A. M.,Delange, F. (1988). Increased recall rate at screening for congenital hypothyroidism in breast fed infants born to iodine overloaded mothers Arch Dis Child, 63(10), 1207-10 | Study design, Intervention/exposure
415 | Chan-Yeung, M.,Ferguson, A.,Watson, A.,Dimich, WArd H.,Dybuncio, A.,Rousseau, R.,Becker, A. (2005). Breastfeeding and risk of asthma and other allergic diseases at aged 7 years in a high-risk birth-cohort [Abstract] American Thoracic Society 2005 International Conference; May 20-25; San Diego, California, #volume#(#issue#), [C49] [Poster: A85] | Publication status
416 | Chan-Yeung, M.,Ferguson, A.,Watson, W.,Dimich-Ward, H.,Rousseau, R.,Lilley, M.,Dybuncio, A.,Becker, A. (2005). The Canadian Childhood Asthma Primary Prevention Study: outcomes at 7 years of age J Allergy Clin Immunol, 116(1), 49-55 | Intervention/exposure
417 | Chan-Yeung, M.,Manfreda, J.,Dimich-Ward, H.,Ferguson, A.,Watson, W.,Becker, A. (2000). A randomized controlled study on the effectiveness of a multifaceted intervention program in the primary prevention of asthma in high-risk infants Arch Pediatr Adolesc Med, 154(7), 657-63 | Intervention/exposure
418 | Chan-Yip, A.,Gray-Donald, K. (1987). Prevalence of iron deficiency among Chinese children aged 6 to 36 months in Montreal CMAJ, 136(4), 373-8 | Intervention/exposure
419 | Chaparro, C. M.,Neufeld, L. M.,Tena Alavez, G.,Eguia-Liz Cedillo, R.,Dewey, K. G. (2006). Effect of timing of umbilical cord clamping on iron status in Mexican infants: a randomised controlled trial Lancet, 367(9527), 1997-2004 | Intervention/exposure
420 | Chapman NL,Barnett DC (1982). In defense of bottle-feeding J Pract Nurs, 32(#issue#), 24-7, 38 | Study design
421 | Chapman, D. J. (2011). Breastfeeding, brain imaging, and maternal behavior J Hum Lact, 27(3), 304-5 | Study design, Outcome
422 | Chapman, D. J. (2012). Exclusive breastfeeding through 6 months: infant intake and growth patterns J Hum Lact, 28(2), 132-3 | Study design
423 | Chapman, D. J. (2012). Longer cumulative breastfeeding duration associated with improved bone strength J Hum Lact, 28(1), 18-9 | Study design
424 | Chapman, D. J. (2013). Does breastfeeding result in smarter children? A closer look J Hum Lact, 29(4), 444-5 | Study design
425 | Chapman, D. J.,Morel, K.,Bermudez-Millan, A.,Young, S.,Damio, G.,Perez-Escamilla, R. (2013). Breastfeeding education and support trial for overweight and obese women: a randomized trial Pediatrics, 131(1), e162-70 | Intervention/exposure, Outcome
426 | Chapman, D. J.,Nommsen-Rivers, L. (2012). Impact of maternal nutritional status on human milk quality and infant outcomes: an update on key nutrients Adv Nutr, 3(3), 351-2 | Study design
427 | Chatzimichael, A.,Tsalkidis, A.,Cassimos, D.,Gardikis, S.,Tripsianis, G.,Deftereos, S.,Ktenidou-Kartali, S.,Tsanakas, I. (2007). The role of breastfeeding and passive smoking on the development of severe bronchiolitis in infants Minerva Pediatr, 59(3), 199-206 | Participant health
428 | Chavalittamrong, B.,Jirapinyo, P. (1987). The weight of Thai infants exclusively breast-fed and formula-fed from birth to four months J Med Assoc Thai, 70(5), 247-51 | Outcome
429 | Chavez-Payan, P.,Grineski, S. E.,Collins, T. W. (2015). Early Life and Environmental Risk Factors Modify the Effect of Acculturation on Hispanic Children’s Asthma Hisp Health Care Int, 13(3), 119-30 | Study design
430 | Chellakooty, M.,Juul, A.,Boisen, K. A.,Damgaard, I. N.,Kai, C. M.,Schmidt, I. M.,Petersen, J. H.,Skakkebæk, N. E.,Main, K. M. (2006). A prospective study of serum insulin-like growth factor I (IGF-I) and IGF-binding protein-3 in 942 healthy infants: Associations with birth weight, gender, growth velocity, and breastfeeding Journal of Clinical Endocrinology and Metabolism, 91(3), 820-826 | Study design, Outcome
431 | Chen, A.,Rogan, W. J. (2004). Breastfeeding and the risk of postneonatal death in the United States Pediatrics, 113(5), e435-9 | Outcome
432 | Chen, B. Y.,Chan, C. C.,Han, Y. Y.,Wu, H. P.,Guo, Y. L. (2012). The risk factors and quality of life in children with allergic rhinitis in relation to seasonal attack patterns Paediatr Perinat Epidemiol, 26(2), 146-55 | Study design
433 | Chen, C. F.,Hsu, M. C.,Shen, C. H.,Wang, C. L.,Chang, S. C.,Wu, K. G.,Wu, S. C.,Chen, S. J. (2011). Influence of breast-feeding on weight loss, jaundice, and waste elimination in neonates Pediatr Neonatol, 52(2), 85-92 | Outcome
434 | Chen, C. J.,Wu, F. T.,Hsiung, C. A.,Chang, W. C.,Wu, H. S.,Wu, C. Y.,Lin, J. S.,Huang, F. C.,Huang, Y. C. (2012). Risk factors for salmonella gastroenteritis in children less than five years of age in Taiwan Pediatr Infect Dis J, 31(12), e239-43 | Outcome
435 | Chen, K.,Chai, L.,Li, H.,Zhang, Y.,Xie, H. M.,Shang, J.,Tian, W.,Yang, P.,Jiang, A. C. (2015). Effect of bovine lactoferrin from iron-fortified formulas on morbidity of diarrhea and respiratory tract infections of weaned infants in a randomized controlled trial Nutrition, #volume#(#issue#), #Pages# | Outcome
436 | Chen, M. (2005). Test a model of breast-feeding duration for Vietnamese mothers in Taiwan Communicating Nursing Research, 38(#issue#), 461-461 1p | Study design
437 | Chen, S. M.,Du, J. W.,Jin, Y. M.,Qiu, L.,Du, Z. H.,Li, D. D.,Chen, H. Y.,Watanabe, C.,Umezaki, M. (2015). Risk Factors for Severe Hand-Foot-Mouth Disease in Children in Hainan, China, 2011-2012 Asia Pac J Public Health, 27(7), 715-22 | Intervention/exposure, Outcome
438 | Chen, X. C.,Liu, D. S.,Fu, A. Z.,Yan, H. C.,Yin, T. A.,Jing, Y. S.,Xu, Q. M. (1989). A longitudinal study on infant growth during the first sixth months of life, in relation to the nutrition of the lactating mothers and to the breastmilk output Prog Food Nutr Sci, 13(2), 113-37 | Intervention/exposure
439 | Chen, Y. (1989). Synergistic effect of passive smoking and artificial feeding on hospitalization for respiratory illness in early childhood Chest, 95(5), 1004-7 | Study design
440 | Chen, Y. (1994). Relationship between type of infant feeding and hospitalization for gastroenteritis in Shanghai infants J Hum Lact, 10(3), 177-9 | Study design
441 | Chen, Y. C.,Tsai, C. H.,Lee, Y. (2012). Gestational medication use, birth conditions, and early postnatal exposures for childhood asthma Clin Dev Immunol, 2012(#issue#), 913426 | Intervention/exposure
442 | Chen, Y.,Yu, S. Z.,Li, W. X. (1988). Artificial feeding and hospitalization in the first 18 months of life Pediatrics, 81(1), 58-62 | Outcome
443 | Cheng, S.,Volgyi, E.,Tylavsky, F. A.,Lyytikainen, A.,Tormakangas, T.,Xu, L.,Cheng, S. M.,Kroger, H.,Alen, M.,Kujala, U. M. (2009). Trait-specific tracking and determinants of body composition: a 7-year follow-up study of pubertal growth in girls BMC Med, 7(#issue#), 5 | Outcome
444 | Cherian, A.,Lawande, R. V. (1987). Diarrhoeal disease in bottle fed children J R Soc Health, 107(2), 62-3 | Country
445 | Chertok, I. R.,Raz, I.,Shoham, I.,Haddad, H.,Wiznitzer, A. (2009). Effects of early breastfeeding on neonatal glucose levels of term infants born to women with gestational diabetes J Hum Nutr Diet, 22(2), 166-9 | Study design, Intervention/exposure
446 | Chertok, I. R.,Shoham-Vardi, I. (2008). Infant hospitalization and breastfeeding post-caesarean section Br J Nurs, 17(12), 786-91 | Outcome
447 | Chesney, R. W. (2003). Rickets: an old form for a new century Pediatr Int, 45(5), 509-11 | Study design
448 | Chhonker, D.,Faridi, M. M.,Narang, M.,Sharma, S. B. (2015). Does type of feeding in infancy influence lipid profile in later life? Indian J Pediatr, 82(4), 345-8 | Country
449 | Chiasson, M. A.,Scheinmann, R.,Hartel, D.,McLeod, N.,Sekhobo, J.,Edmunds, L. S.,Findley, S. (2015). Predictors of Obesity in a Cohort of Children Enrolled in WIC as Infants and Retained to 3 Years of Age J Community Health, #volume#(#issue#), #Pages# | Intervention/exposure
450 | Chierici, R.,Sawatzki, G.,Tamisari, L.,Volpato, S.,Vigi, V. (1992). Supplementation of an adapted formula with bovine lactoferrin. 2. Effects on serum iron, ferritin and zinc levels Acta Paediatr, 81(6-7), 475-9 | Study design, Size of study groups
451 | Chierici, R.,Sawatzki, G.,Thurl, S.,Tovar, K.,Vigi, V. (1997). Experimental milk formulae with reduced protein content and desialylated milk proteins: influence on the faecal flora and the growth of term newborn infants Acta Paediatr, 86(6), 557-63 | Size of study groups
452 | Chin, K. C.,Galea, P.,Goel, K. M. (1981). Changing pattern in infant feeding practices Health Bull (Edinb), 39(1), 51-7 | Outcome
453 | Chiu, W. C.,Liao, H. F.,Chang, P. J.,Chen, P. C.,Chen, Y. C. (2011). Duration of breast feeding and risk of developmental delay in Taiwanese children: a nationwide birth cohort study Paediatr Perinat Epidemiol, 25(6), 519-27 | Study design
454 | Chivers, P.,Hands, B.,Parker, H.,Bulsara, M.,Beilin, L. J.,Kendall, G. E.,Oddy, W. H. (2010). Body mass index, adiposity rebound and early feeding in a longitudinal cohort (Raine Study) Int J Obes (Lond), 34(7), 1169-76 | Intervention/exposure
455 | Chmiel, R.,Beyerlein, A.,Knopff, A.,Hummel, S.,Ziegler, A. G.,Winkler, C. (2015). Early infant feeding and risk of developing islet autoimmunity and type 1 diabetes Acta Diabetol, 52(3), 621-4 | Outcome
456 | Chomtho, S. (2014). Breastfeeding to prevent double burden of malnutrition Southeast Asian J Trop Med Public Health, 45 Suppl 1(#issue#), 132-6 | Study design
457 | Chong, H. L.,Soo, T. L.,Rasat, R. (2012). Childhood obesity-prevalence among 7 and 8 year old primary school students in Kota Kinabalu Medical Journal of Malaysia, 67(2), 147-150 | Study design
458 | Christopher, G. C. (2009). First food: the essential role of breastfeeding Breastfeed Med, 4 Suppl 1(#issue#), S9-s10 | Study design
459 | Chu, L.,Retnakaran, R.,Zinman, B.,Hanley, A. J. G.,Hamilton, J. K. (2012). Impact of maternal physical activity and infant feeding practices on infant weight gain and adiposity International Journal of Endocrinology, 2012(#issue#), #Pages# | Intervention/exposure
460 | Chuang, C. H.,Hsieh, W. S.,Chen, Y. C.,Chang, P. J.,Hurng, B. S.,Lin, S. J.,Chen, P. C. (2011). Infant feeding practices and physician diagnosed atopic dermatitis: a prospective cohort study in Taiwan Pediatr Allergy Immunol, 22(1 Pt 1), 43-9 | Outcome
461 | Chuansumrit, A.,Arnutti, P.,Apivanich, S. (2002). Iron status of one-year-old infants in a well baby clinic J Med Assoc Thai, 85 Suppl 4(#issue#), S1081-8 | Study design, Size of study groups
462 | Chye, J. K.,Lim, C. T. (1998). Breastfeeding at 6 months and effects on infections Singapore Med J, 39(12), 551-6 | Outcome
463 | Ciardelli, R.,Haumont, D.,Gnat, D.,Vertongen, F.,Delange, F. (2002). The nutritional iodine supply of Belgian neonates is still insufficient Eur J Pediatr, 161(10), 519-23 | Intervention/exposure
464 | Cilleruelo, M. L.,Fernandez-Fernandez, S.,Jimenez-Jimenez, J.,Rayo, A. I.,Larramendi, C. H. (2015). Prevalence and Natural History of Celiac Disease in a Cohort of at-Risk Children J Pediatr Gastroenterol Nutr, #volume#(#issue#), #Pages# | Study design
465 | Ciria-Martin, A.,Caravia-Bernardo, F.,Alvarez-Castello, M.,Insua-Arregui, C.,Tamargo-Barbeito, T. O.,Massip-Nicot, J. (2012). [Risk factors for recurrent upper airways infections in pre-school children] Rev Alerg Mex, 59(3), 113-22 | Language
466 | Civelek, E.,Cakir, B.,Orhan, F.,Yuksel, H.,Boz, A. B.,Uner, A.,Sekerel, B. E. (2011). Risk factors for current wheezing and its phenotypes among elementary school children Pediatr Pulmonol, 46(2), 166-74 | Study design
467 | Clark MJ (1984). A case for breast feeding Ky Nurse, 32(#issue#), 14-5 | Study design
468 | Clark, K. M.,Castillo, M.,Calatroni, A.,Walter, T.,Cayazzo, M.,Pino, P.,Lozoff, B. (2006). Breast-feeding and mental and motor development at 51/2 years Ambul Pediatr, 6(2), 65-71 | Intervention/exposure
469 | Clark-Kellerman, M. J. (1985). A case for formula feeding Ky Nurse, 33(3), 13-4 | Study design
470 | Clavano, N. R. (1982). Mode of feeding and its effect on infant mortality and morbidity J Trop Pediatr, 28(6), 287-93 | Country
471 | Closa-Monasterolo, R.,Gispert-Llaurado, M.,Luque, V.,Ferre, N.,Rubio-Torrents, C.,Zaragoza-Jordana, M.,Escribano, J. (2013). Safety and efficacy of inulin and oligofructose supplementation in infant formula: results from a randomized clinical trial Clin Nutr, 32(6), 918-27 | Intervention/exposure, Outcome
472 | Close, C. (1987). Babies, bottles, and boobs Br Med J (Clin Res Ed), 295(6613), 1666-7 | Study design
473 | Cochi, S. L.,Fleming, D. W.,Hightower, A. W.,Limpakarnjanarat, K.,Facklam, R. R.,Smith, J. D.,Sikes, R. K.,Broome, C. V. (1986). Primary invasive Haemophilus influenzae type b disease: a population-based assessment of risk factors J Pediatr, 108(6), 887-96 | Outcome
474 | Cockburn F,Belton NR,Purvis RJ,Giles MM,Brown JK,Turner TL,Wilkinson EM,Forfar JO,Barrie WJ,McKay GS,Pocock SJ (1980). Maternal vitamin D intake and mineral metabolism in mothers and their newborn infants Br Med J, 281(#issue#), 11-4 | Size of study groups, Intervention/exposure
475 | Cockburn, F. (1994). Neonatal brain and dietary lipids Arch Dis Child Fetal Neonatal Ed, 70(1), F1-2 | Study design
476 | Codispoti, C. D.,Levin, L.,LeMasters, G. K.,Ryan, P.,Reponen, T.,Villareal, M.,Burkle, J.,Stanforth, S.,Lockey, J. E.,Khurana Hershey, G. K.,Bernstein, D. I. (2010). Breast-feeding, aeroallergen sensitization, and environmental exposures during infancy are determinants of childhood allergic rhinitis J Allergy Clin Immunol, 125(5), 1054-1060 e1 | Outcome
477 | Cogswell, J. J.,Mitchell, E. B.,Alexander, J. (1987). Parental smoking, breast feeding, and respiratory infection in development of allergic diseases Arch Dis Child, 62(4), 338-44 | Intervention/exposure
478 | Colchero, M. A.,Contreras-Loya, D.,Lopez-Gatell, H.,Gonzalez de Cosio, T. (2015). The costs of inadequate breastfeeding of infants in Mexico Am J Clin Nutr, 101(3), 579-86 | Study design
479 | Colen, C. G.,Ramey, D. M. (2014). Is breast truly best? Estimating the effects of breastfeeding on long-term child health and wellbeing in the United States using sibling comparisons Soc Sci Med, 109(#issue#), 55-65 | Outcome
480 | Collipp, P. J.,Kuo, B.,Castro-Magana, M.,Chen, S. Y.,Salvatore, S. (1983). Hair zinc levels in infants Clin Pediatr (Phila), 22(7), 512-3 | Study design
481 | Cone, T. E., Jr. (1981). The nursing bottle caries syndrome JAMA, 245(22), 2334 | Study design
482 | Connolly, C. (2005). Saving babies: child-saving and infant nutrition Pediatr Nurs, 31(4), 309-11 | Study design
483 | Connor, S. L.,Zhu, N.,Anderson, G. J.,Hamill, D.,Jaffe, E.,Carlson, J.,Connor, W. E. (2000). Cheek cell phospholipids in human infants: a marker of docosahexaenoic and arachidonic acids in the diet, plasma, and red blood cells Am J Clin Nutr, 71(1), 21-7 | Size of study groups
484 | Conover B (1992). Exposures during pregnancy and lactation Nebr Med J, 77(#issue#), 65-7 | Study design
485 | Coombes R (1999). Bottling out over formula feed Nurs Times, 95(#issue#), 12-3 | Study design
486 | Coppi, S.,Iacoponi, F.,Fommei, C.,Strambi, M. (2013). Growth trend during the first six months of life in male infants with different type of feeding Minerva Pediatr, 65(1), 51-9 | Outcome
487 | Cornish, R. P.,Tilling, K.,Boyd, A.,Davies, A.,Macleod, J. (2015). Using linked educational attainment data to reduce bias due to missing outcome data in estimates of the association between the duration of breastfeeding and IQ at 15 years Int J Epidemiol, 44(3), 937-45 | Outcome
488 | Corrao, G.,Tragnone, A.,Caprilli, R.,Trallori, G.,Papi, C.,Andreoli, A.,Di Paolo, M.,Riegler, G.,Rigo, G. P.,Ferrau, O.,Mansi, C.,Ingrosso, M.,Valpiani, D. (1998). Risk of inflammatory bowel disease attributable to smoking, oral contraception and breastfeeding in Italy: a nationwide case-control study. Cooperative Investigators of the Italian Group for the Study of the Colon and the Rectum (GISC) Int J Epidemiol, 27(3), 397-404 | Intervention/exposure
489 | Correa-Faria, P.,Martins-Junior, P. A.,Vieira-Andrade, R. G.,Marques, L. S.,Ramos-Jorge, M. L. (2013). Perinatal factors associated with developmental defects of enamel in primary teeth: a case-control study Braz Oral Res, 27(4), 363-8 | Outcome
490 | Corvalan, C.,Kain, J.,Weisstaub, G.,Uauy, R. (2009). Impact of growth patterns and early diet on obesity and cardiovascular risk factors in young children from developing countries Proc Nutr Soc, 68(3), 327-37 | Study design
491 | Corvalan, C.,Uauy, R.,Stein, A. D.,Kain, J.,Martorell, R. (2009). Effect of growth on cardiometabolic status at 4 y of age Am J Clin Nutr, 90(3), 547-55 | Study design
492 | Costeira, M. J.,Oliveira, P.,Ares, S.,de Escobar, G. M.,Palha, J. A. (2009). Iodine status of pregnant women and their progeny in the Minho Region of Portugal Thyroid, 19(2), 157-63 | Size of study groups, Intervention/exposure
493 | Counsilman, J. J.,Chan, S. Y.,Haiyon, H.,Rahim, N. A.,Salim, R.,Tai, T. Y.,Tan, M. L.,Zainy, Z.,Viegas, O. (1986). Breast feeding among poor Singaporeans J Trop Pediatr, 32(6), 310-2 | Outcome
494 | Counsilman, J. J.,Chua, S.,Viegas, O. (1986). Breast feeding among well-to-do Singaporeans J Trop Pediatr, 32(6), 313-6 | Outcome
495 | Counter, S. A.,Buchanan, L. H.,Ortega, F. (2004). Current pediatric and maternal lead levels in blood and breast milk in Andean inhabitants of a lead-glazing enclave J Occup Environ Med, 46(9), 967-73 | Study design, Intervention/exposure
496 | Couper, J. J.,Beresford, S.,Hirte, C.,Baghurst, P. A.,Pollard, A.,Tait, B. D.,Harrison, L. C.,Colman, P. G. (2009). Weight gain in early life predicts risk of islet autoimmunity in children with a first-degree relative with type 1 diabetes Diabetes Care, 32(1), 94-9 | Outcome
497 | Couper, J. J.,Steele, C.,Beresford, S.,Powell, T.,McCaul, K.,Pollard, A.,Gellert, S.,Tait, B.,Harrison, L. C.,Colman, P. G. (1999). Lack of association between duration of breast-feeding or introduction of cow’s milk and development of islet autoimmunity Diabetes, 48(11), 2145-9 | Outcome
498 | Courage, M. L.,McCloy, U. R.,Herzberg, G. R.,Andrews, W. L.,Simmons, B. S.,McDonald, A. C.,Mercer, C. N.,Friel, J. K. (1998). Visual acuity development and fatty acid composition of erythrocytes in full-term infants fed breast milk, commercial formula, or evaporated milk J Dev Behav Pediatr, 19(1), 9-17 | Outcome
499 | Cowden, M. (1982). Infant feeding Midwives Chron, 95(1136), 319-20 | Study design
500 | Crestani, A. H.,Souza, A. P.,Beltrami, L.,Moraes, A. B. (2012). Analysis of the association among types of breastfeeding, presence of child development risk, socioeconomic and obstetric variables J Soc Bras Fonoaudiol, 24(3), 205-10 | Study design, Outcome
501 | Crewe, E.,Murphy, A. M. (1980). Further studies on neonatal rotavirus infections Med J Aust, 1(2), 61-3 | Study design, Outcome
502 | Crocker, B.,Green, T. J.,Barr, S. I.,Beckingham, B.,Bhagat, R.,Dabrowska, B.,Douthwaite, R.,Evanson, C.,Friesen, R.,Hydamaka, K.,Li, W.,Simmons, K.,Tse, L. (2011). Very high vitamin D supplementation rates among infants aged 2 months in Vancouver and Richmond, British Columbia, Canada BMC Public Health, 11(#issue#), 905 | Study design, Outcome
503 | Crossland, D. S.,Richmond, S.,Hudson, M.,Smith, K.,Abu-Harb, M. (2008). Weight change in the term baby in the first 2 weeks of life Acta Paediatr, 97(4), 425-9 | Outcome
504 | Crouch, A. A.,Seow, W. K.,Whitman, L. M.,Thong, Y. H. (1991). Effect of human milk and infant milk formulae on adherence of Giardia intestinalis Trans R Soc Trop Med Hyg, 85(5), 617-9 | Non-human sample, Intervention/exposure
505 | Crouch, S.,Lightfoot, T.,Simpson, J.,Smith, A.,Ansell, P.,Roman, E. (2012). Infectious illness in children subsequently diagnosed with acute lymphoblastic leukemia: modeling the trends from birth to diagnosis Am J Epidemiol, 176(5), 402-8 | Intervention/exposure
506 | Crow, D. R. (1992). Baby bottle tooth decay prevention--a new program for the Texas Department of Health Tex Dent J, 109(8), 141 | Study design
507 | Croxatto, H. B.,Diaz, S.,Peralta, O.,Juez, G.,Herreros, C.,Casado, M. E.,Salvatierra, A. M.,Miranda, P.,Duran, E. (1983). Fertility regulation in nursing women: IV. Long-term influence of a low-dose combined oral contraceptive initiated at day 30 postpartum upon lactation and infant growth Contraception, 27(1), 13-25 | Intervention/exposure
508 | Crume, T. L.,Bahr, T. M.,Mayer-Davis, E. J.,Hamman, R. F.,Scherzinger, A. L.,Stamm, E.,Dabelea, D. (2012). Selective protection against extremes in childhood body size, abdominal fat deposition, and fat patterning in breastfed children Arch Pediatr Adolesc Med, 166(5), 437-43 | Study design
509 | Crume, T. L.,Ogden, L. G.,Mayer-Davis, E. J.,Hamman, R. F.,Norris, J. M.,Bischoff, K. J.,McDuffie, R.,Dabelea, D. (2012). The impact of neonatal breast-feeding on growth trajectories of youth exposed and unexposed to diabetes in utero: the EPOCH Study Int J Obes (Lond), 36(4), 529-34 | Intervention/exposure
510 | Crume, T. L.,Ogden, L.,Maligie, M.,Sheffield, S.,Bischoff, K. J.,McDuffie, R.,Daniels, S.,Hamman, R. F.,Norris, J. M.,Dabelea, D. (2011). Long-term impact of neonatal breastfeeding on childhood adiposity and fat distribution among children exposed to diabetes in utero Diabetes Care, 34(3), 641-5 | Study design, Intervention/exposure
511 | Cruz, M. L.,Wong, W. W.,Mimouni, F.,Hachey, D. L.,Setchell, K. D.,Klein, P. D.,Tsang, R. C. (1994). Effects of infant nutrition on cholesterol synthesis rates Pediatr Res, 35(2), 135-40 | Size of study groups
512 | Cuhaci Çakir, B.,Beyazova, U.,Kemalo?lu, Y. K.,Özkan, S.,Gündüz, B.,Özdek, A. (2012). Effectiveness of pandemic influenza A/H1N1 vaccine for prevention of otitis media in children European journal of pediatrics, 171(11), 1667-71 | Intervention/exposure
513 | Cullinan, T. R.,Saunders, D. I. (1983). Prediction of infant hospital admission risk Arch Dis Child, 58(6), 423-7 | Study design, Intervention/exposure
514 | Cunningham, A. S. (1987). Breast-feeding and health J Pediatr, 110(4), 658-9 | Study design
515 | Curtis, J. A.,Kooh, S. W.,Fraser, D.,Greenberg, M. L. (1983). Nutritional rickets in vegetarian children Can Med Assoc J, 128(2), 150-2 | Study design
516 | Cushing, A. H.,Anderson, L. (1982). Diarrhea in breast-fed and non-breast-fed infants Pediatrics, 70(6), 921-5 | Size of study groups
517 | Cushing, A. H.,Samet, J. M.,Lambert, W. E.,Skipper, B. J.,Hunt, W. C.,Young, S. A.,McLaren, L. C. (1998). Breastfeeding reduces risk of respiratory illness in infants Am J Epidemiol, 147(9), 863-70 | Outcome
518 | Cutting, W. A. (2002). Cholera and breastfeeding Trop Doct, 32(1), 57-8 | Study design
519 | da Costa Lima, R.,Victora, C. G.,Menezes, A. M.,Barros, F. C. (2003). Do risk factors for childhood infections and malnutrition protect against asthma? A study of Brazilian male adolescents Am J Public Health, 93(11), 1858-64 | Outcome
520 | Dada, J. H. (2010). Nutrition and type 1 diabetes: can diet reduce risk? Today’s Dietitian, 12(8), 36-39 4p | Study design
521 | Dadhich, J. P.,Agarwal, R. K. (2009). Mainstreaming early and exclusive breastfeeding for improving child survival Indian Pediatr, 46(1), 11-7 | Country, Study design
522 | Daga, S. R. (1989). Reduction in neonatal mortality by simple interventions J Biosoc Sci Suppl, 10(#issue#), 127-36 | Country
523 | Daga, S. R.,Daga, A. S. (1989). Reduction in neonatal mortality with simple interventions J Trop Pediatr, 35(4), 191-6 | Country, Study design
524 | Dagan, R.,Pridan, H. (1982). Relationship of breast feeding versus bottle feeding with emergency room visits and hospitalization for infectious diseases Eur J Pediatr, 139(3), 192-4 | Outcome
525 | Dahlquist, G.,Blom, L.,Lonnberg, G. (1991). The Swedish Childhood Diabetes Study--a multivariate analysis of risk determinants for diabetes in different age groups Diabetologia, 34(10), 757-62 | Outcome
526 | Dahlquist, G.,Mustonen, L. (2000). Analysis of 20 years of prospective registration of childhood onset diabetes time trends and birth cohort effects. Swedish Childhood Diabetes Study Group Acta Paediatr, 89(10), 1231-7 | Study design, Intervention/exposure
527 | Dahlquist, G.,Savilahti, E.,Landin-Olsson, M. (1992). An increased level of antibodies to β-lactoglobulin is a risk determinant for early-onset Type 1 (insulin-dependent) diabetes mellitus independent of islet cell antibodies and early introduction of cow’s milk Diabetologia, 35(10), 980-984 | Intervention/exposure, Outcome
528 | Dallaire, R.,Muckle, G.,Rouget, F.,Kadhel, P.,Bataille, H.,Guldner, L.,Seurin, S.,Chajes, V.,Monfort, C.,Boucher, O.,Thome, J. P.,Jacobson, S. W.,Multigner, L.,Cordier, S. (2012). Cognitive, visual, and motor development of 7-month-old Guadeloupean infants exposed to chlordecone Environ Res, 118(#issue#), 79-85 | Study design, Intervention/exposure
529 | Dalmeijer, G. W.,Wijga, A. H.,Gehring, U.,Renders, C. M.,Koppelman, G. H.,Smit, H. A.,van Rossem, L. (2015). Fatty acid composition in breastfeeding and school performance in children aged 12 years Eur J Nutr, #volume#(#issue#), #Pages# | Outcome
530 | Daly, K. A.,Rich, S. S.,Levine, S.,Margolis, R. H.,Le, C. T.,Lindgren, B.,Giebink, G. S. (1996). The family study of otitis media: design and disease and risk factor profiles Genet Epidemiol, 13(5), 451-68 | Study design, Participant health
531 | Damore, D.,Mansbach, J. M.,Clark, S.,Ramundo, M.,Camargo, C. A., Jr. (2008). Prospective multicenter bronchiolitis study: predicting intensive care unit admissions Acad Emerg Med, 15(10), 887-94 | Study design
532 | Daniels, L. A.,Mallan, K. M.,Nicholson, J. M.,Battistutta, D.,Magarey, A. (2013). Outcomes of an early feeding practices intervention to prevent childhood obesity Pediatrics, 132(1), e109-e118 | Intervention/exposure
533 | Darmstadt, G. L.,Munar, W. (2013). Behavior change and community participation: Assessing causal pathways affecting neonatal mortality JAMA - Journal of the American Medical Association, 310(9), 969-70 | Study design
534 | Darnall, B. D.,Schatman, M. E. (2015). Protecting the infant from unknown risks Pain Med, 16(4), 631-2 | Study design
535 | DaVanzo, J.,Habicht, J. P. (1986). Infant mortality decline in Malaysia, 1946-1975: the roles of changes in variables and changes in the structure of relationships Demography, 23(2), 143-60 | Study design, Intervention/exposure
536 | Davanzo, R.,Cannioto, Z.,Ronfani, L.,Monasta, L.,Demarini, S. (2013). Breastfeeding and neonatal weight loss in healthy term infants J Hum Lact, 29(1), 45-53 | Intervention/exposure
537 | David, C. B.,David, P. H.,el Lozy, M. (1983). Determinants of breastfeeding duration and nutrition in a transition society J Trop Pediatr, 29(1), 45-9 | Country
538 | Davidson, R.,Roberts, S. E.,Wotton, C. J.,Goldacre, M. J. (2010). Influence of maternal and perinatal factors on subsequent hospitalisation for asthma in children: evidence from the Oxford record linkage study BMC Pulm Med, 10(#issue#), 14 | Intervention/exposure
539 | Davis, D. W.,Bell, P. A. (1991). Infant feeding practices and occlusal outcomes: a longitudinal study J Can Dent Assoc, 57(7), 593-4 | Outcome
540 | Davis, J. (2014). Well advised: a journey to breastfeeding success Pract Midwife, 17(8), 34, 36-8 | Study design
541 | Davis, J. N.,Gunderson, E. P.,Gyllenhammer, L. E.,Goran, M. I. (2013). Impact of gestational diabetes mellitus on pubertal changes in adiposity and metabolic profiles in Latino offspring J Pediatr, 162(4), 741-5 | Study design, Intervention/exposure
542 | Davis, J. N.,Weigensberg, M. J.,Shaibi, G. Q.,Crespo, N. C.,Kelly, L. A.,Lane, C. J.,Goran, M. I. (2007). Influence of breastfeeding on obesity and type 2 diabetes risk factors in Latino youth with a family history of type 2 diabetes Diabetes Care, 30(4), 784-9 | Outcome
543 | Davis, J. N.,Whaley, S. E.,Goran, M. I. (2012). Effects of breastfeeding and low sugar-sweetened beverage intake on obesity prevalence in Hispanic toddlers Am J Clin Nutr, 95(1), 3-8 | Study design
544 | Davis, J. R., Jr.,Goldenring, J.,Lubin, B. H. (1981). Nutritional vitamin B12 deficiency in infants Am J Dis Child, 135(6), 566-7 | Study design
545 | Davis, M. K.,Savitz, D. A.,Graubard, B. I. (1988). Infant feeding and childhood cancer Lancet, 2(8607), 365-8 | Outcome
546 | Davis, R. E.,Icke, G. C.,Hilton, J. M.,Orr, E. (1986). Serum thiamin, pyridoxal, cobalamin and folate concentrations in young infants Acta Paediatr Scand, 75(3), 402-7 | Study design, Intervention/exposure
547 | Dawodu, A.,Davidson, B.,Woo, J. G.,Peng, Y. M.,Ruiz-Palacios, G. M.,de Lourdes Guerrero, M.,Morrow, A. L. (2015). Sun exposure and vitamin D supplementation in relation to vitamin D status of breastfeeding mothers and infants in the global exploration of human milk study Nutrients, 7(2), 1081-93 | Intervention/exposure
548 | Dawodu, A.,Zalla, L.,Woo, J. G.,Herbers, P. M.,Davidson, B. S.,Heubi, J. E.,Morrow, A. L. (2014). Heightened attention to supplementation is needed to improve the vitamin D status of breastfeeding mothers and infants when sunshine exposure is restricted Matern Child Nutr, 10(3), 383-97 | Intervention/exposure
549 | de Beer, M.,Vrijkotte, T. G.,Fall, C. H.,van Eijsden, M.,Osmond, C.,Gemke, R. J. (2015). Associations of infant feeding and timing of linear growth and relative weight gain during early life with childhood body composition Int J Obes (Lond), 39(4), 586-92 | Intervention/exposure
550 | de Boer, R. (2011). A topic in 10 questions: assessing common dietary deficiencies J Fam Health Care, 21(6), 28-9 | Study design
551 | de Bruin, N. C.,Degenhart, H. J.,Gal, S.,Westerterp, K. R.,Stijnen, T.,Visser, H. K. (1998). Energy utilization and growth in breast-fed and formula-fed infants measured prospectively during the first year of life Am J Clin Nutr, 67(5), 885-96 | Size of study groups
552 | de Fátima Buco Busto Moreno, Patrícia,Trombini Schmidt, Kayna (2014). BREAST-FEEDING AND FACTORS RELATED TO EARLY WEANING Cogitare Enfermagem, 19(3), 531-537 7p | Size of study groups, Outcome
553 | de Freitas, C. L.,Romani, S.,Amigo, H. (1986). Breast-feeding and malnutrition in rural areas of northeast Brazil Bull Pan Am Health Organ, 20(2), 138-46 | Study design, Outcome
554 | de Hoog, M. L.,van Eijsden, M.,Stronks, K.,Gemke, R. J.,Vrijkotte, T. G. (2011). The role of infant feeding practices in the explanation for ethnic differences in infant growth: the Amsterdam Born Children and their Development study Br J Nutr, 106(10), 1592-601 | Outcome
555 | de Jong, C.,Boehm, G.,Kikkert, H. K.,Hadders-Algra, M. (2011). The Groningen LCPUFA study: No effect of short-term postnatal long-chain polyunsaturated fatty acids in healthy term infants on cardiovascular and anthropometric development at 9 years Pediatr Res, 70(4), 411-6 | Outcome
556 | de Jong, C.,Kikkert, H. K.,Fidler, V.,Hadders-Algra, M. (2010). The Groningen LCPUFA study: no effect of postnatal long-chain polyunsaturated fatty acids in healthy term infants on neurological condition at 9 years Br J Nutr, 104(4), 566-72 | Outcome
557 | de Jong, C.,Kikkert, H. K.,Fidler, V.,Hadders-Algra, M. (2012). Effects of long-chain polyunsaturated fatty acid supplementation of infant formula on cognition and behaviour at 9 years of age Dev Med Child Neurol, 54(12), 1102-8 | Outcome
558 | de Jonge, L. L.,Langhout, M. A.,Taal, H. R.,Franco, O. H.,Raat, H.,Hofman, A.,van Osch-Gevers, L.,Jaddoe, V. W. (2013). Infant feeding patterns are associated with cardiovascular structures and function in childhood J Nutr, 143(12), 1959-65 | Outcome
559 | de Jonge, L. L.,van Osch-Gevers, L.,Geelhoed, J. J.,Hofman, A.,Steegers, E. A.,Helbing, W. A.,Jaddoe, V. W. (2010). Breastfeeding is not associated with left cardiac structures and blood pressure during the first two years of life. The Generation R Study Early Hum Dev, 86(8), 463-8 | Outcome
560 | De Kroon, M. L.,Renders, C. M.,Buskermolen, M. P.,Van Wouwe, J. P.,van Buuren, S.,Hirasing, R. A. (2011). The Terneuzen Birth Cohort. Longer exclusive breastfeeding duration is associated with leaner body mass and a healthier diet in young adulthood BMC Pediatr, 11(#issue#), 33 | Intervention/exposure
561 | de la Hunty, A. (2009). The EU Childhood Obesity Project Nutrition Bulletin, 34(4), 403-406 4p | Study design, Intervention/exposure
562 | de Lima, L. F.,Barbosa, F., Jr.,Navarro, A. M. (2013). Excess iodinuria in infants and its relation to the iodine in maternal milk J Trace Elem Med Biol, 27(3), 221-5 | Study design, Size of study groups
563 | de Looy, A. E. (1986). Infant nutrition Nursing (Lond), 3(12), 446-9 | Study design
564 | De Lucia Rolfe, E.,Modi, N.,Uthaya, S.,Hughes, I. A.,Dunger, D. B.,Acerini, C.,Stolk, R. P.,Ong, K. K. (2013). Ultrasound estimates of visceral and subcutaneous-abdominal adipose tissues in infancy J Obes, 2013(#issue#), 951954 | Intervention/exposure
565 | de Melo, M. C. N.,Taddei, J. A. A. C.,Diniz-Santos, D. R.,Vieira, C.,Carneiro, N. B.,Melo, R. F.,Silva, L. R. (2008). Incidence of diarrhea in children living in urban slums in Salvador, Brazil Brazilian Journal of Infectious Diseases, 12(1), 89-93 | Intervention/exposure
566 | de Oliveira Bezerra, Joana Lidyanne,De Vasconcelos, Maria Gorete Lucena,Pereira Linhares, Francisca Márcia,Javorski, Marly,Leal, Luciana Pedrosa (2014). Maternal perception of their children’s body image in exclusive breastfeeding Acta Paulista de Enfermagem, 27(4), 293-299 7p | Study design
567 | de Oliveira, D. M.,Dahan, P.,Ferreira, D. F.,de Oliveira, L. F.,de Paula, L. I.,de Figueiredo, A. A.,de Bessa, J., Jr.,Bastos Netto, J. M. (2015). Association between exclusive maternal breastfeeding during the first 4 months of life and primary enuresis J Pediatr Urol, #volume#(#issue#), #Pages# | Outcome
568 | de Rooy, L.,Hawdon, J. (2002). Nutritional factors that affect the postnatal metabolic adaptation of full-term small- and large-for-gestational-age infants Pediatrics, 109(3), E42 | Size of study groups, Outcome
569 | De Souza, A. C.,Petersont, K. E.,Cufino, E.,do Amaral, M. I.,Gardner, J. (2001). Underlying and proximate determinants of diarrhoea-specific infant mortality rates among municipalities in the state of Ceara, north-east Brazil: an ecological study J Biosoc Sci, 33(2), 227-44 | Study design, Intervention/exposure
570 | Deacon C (2001). Breastfeeding. Are we just bottling out? Nurs Times, 97(#issue#), 26-7 | Study design
571 | Decker, E.,Engelmann, G.,Findeisen, A.,Gerner, P.,Laaß, M.,Ney, D.,Posovszky, C.,Hoy, L.,Hornef, M. W. (2010). Cesarean delivery is associated with celiac disease but not inflammatory bowel disease in children Pediatrics, 125(6), e1433-e1440 | Outcome
572 | Decsi, T.,Kelemen, B.,Minda, H.,Burus, I. (2000). Long term effect of breast feeding on essential fatty acid status in healthy, full-term infants Adv Exp Med Biol, 478(#issue#), 397-8 | Study design, Size of study groups
573 | Decsi, T.,Kelemen, B.,Minda, H.,Burus, I.,Kohn, G. (2000). Effect of type of early infant feeding on fatty acid composition of plasma lipid classes in full-term infants during the second 6 months of life J Pediatr Gastroenterol Nutr, 30(5), 547-51 | Size of study groups
574 | Decsi, T.,Koletzko, B. (1995). Growth, fatty acid composition of plasma lipid classes, and plasma retinol and alpha-tocopherol concentrations in full-term infants fed formula enriched with omega-6 and omega-3 long-chain polyunsaturated fatty acids Acta Paediatr, 84(7), 725-32 | Size of study groups, Intervention/exposure
575 | Decsi, T.,Thiel, I.,Koletzko, B. (1995). Essential fatty acids in full term infants fed breast milk or formula Arch Dis Child Fetal Neonatal Ed, 72(1), F23-8 | Size of study groups, Intervention/exposure
576 | Dedoussis, G. V.,Yannakoulia, M.,Timpson, N. J.,Manios, Y.,Kanoni, S.,Scott, R. A.,Papoutsakis, C.,Deloukas, P.,Pitsiladis, Y. P.,Davey-Smith, G.,Hirschhorn, J. N.,Lyon, H. N. (2011). Does a short breastfeeding period protect from FTO-induced adiposity in children? Int J Pediatr Obes, 6(2-2), e326-35 | Study design
577 | Deegan, K. L.,Jones, K. M.,Zuleta, C.,Ramirez-Zea, M.,Lildballe, D. L.,Nexo, E.,Allen, L. H. (2012). Breast milk vitamin B-12 concentrations in Guatemalan women are correlated with maternal but not infant vitamin B-12 status at 12 months postpartum J Nutr, 142(1), 112-6 | Country
578 | Deliu, M.,Belgrave, D.,Simpson, A.,Murray, C. S.,Kerry, G.,Custovic, A. (2014). Impact of rhinitis on asthma severity in school-age children Allergy, 69(11), 1515-21 | Outcome
579 | Dell, S.,To, T. (2001). Breastfeeding and asthma in young children: findings from a population-based study Arch Pediatr Adolesc Med, 155(11), 1261-5 | Study design
580 | De-Lucchi C,Pita ML,Faus MJ,Periago JL,Gil A (1988). Influences of diet and postnatal age on the lipid composition of red blood cell membrane in newborn infants Ann Nutr Metab, 32(#issue#), 231-9 | Study design
581 | DeLucchi, C.,Pita, M. L.,Faus, M. J.,Molina, J. A.,Uauy, R.,Gil, A. (1987). Effects of dietary nucleotides on the fatty acid composition of erythrocyte membrane lipids in term infants J Pediatr Gastroenterol Nutr, 6(4), 568-74 | Size of study groups
582 | Demir, A. U.,Celikel, S.,Karakaya, G.,Kalyoncu, A. F. (2010). Asthma and allergic diseases in school children from 1992 to 2007 with incidence data J Asthma, 47(10), 1128-35 | Study design
583 | Demment, M. M.,Haas, J. D.,Olson, C. M. (2014). Changes in family income status and the development of overweight and obesity from 2 to 15 years: a longitudinal study BMC Public Health, 14(#issue#), 417 | Intervention/exposure
584 | Demmers, T. A.,Jones, P. J.,Wang, Y.,Krug, S.,Creutzinger, V.,Heubi, J. E. (2005). Effects of early cholesterol intake on cholesterol biosynthesis and plasma lipids among infants until 18 months of age Pediatrics, 115(6), 1594-601 | Size of study groups
585 | Dennehy, P. H.,Cortese, M. M.,Begue, R. E.,Jaeger, J. L.,Roberts, N. E.,Zhang, R.,Rhodes, P.,Gentsch, J.,Ward, R.,Bernstein, D. I.,Vitek, C.,Bresee, J. S.,Staat, M. A. (2006). A case-control study to determine risk factors for hospitalization for rotavirus gastroenteritis in U.S. children Pediatr Infect Dis J, 25(12), 1123-31 | Intervention/exposure
586 | Der, G.,Batty, G. D.,Deary, I. J. (2006). Effect of breast feeding on intelligence in children: Prospective study, sibling pairs analysis, and meta-analysis British Medical Journal, 333(7575), 945-948 | Outcome
587 | Derkson, G. D.,Ponti, P. (1982). Nursing bottle syndrome; prevalence and etiology in a non-fluoridated city J Can Dent Assoc, 48(6), 389-93 | Study design
588 | Deshpande, W. (2008). Exclusive breastfeeding for the first six months Community Pract, 81(5), 34-6 | Study design
589 | Dewailly, E.,Ayotte, P.,Bruneau, S.,Gingras, S.,Belles-Isles, M.,Roy, R. (2000). Susceptibility to infections and immune status in Inuit infants exposed to organochlorines Environ Health Perspect, 108(3), 205-11 | Outcome
590 | Dewey, K. G. (2000). Complementary feeding and breastfeeding Pediatrics, 106(5), 1301 | Study design
591 | Dewey, K. G.,Hawck, M. G.,Brown, K. H.,Lartey, A.,Cohen, R. J.,Peerson, J. M. (2005). Infant weight-for-length is positively associated with subsequent linear growth across four different populations Matern Child Nutr, 1(1), 11-20 | Intervention/exposure
592 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B. (1991). Adequacy of energy intake among breast-fed infants in the DARLING study: relationships to growth velocity, morbidity, and activity levels. Davis Area Research on Lactation, Infant Nutrition and Growth J Pediatr, 119(4), 538-47 | Intervention/exposure
593 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B. (1992). Growth of breast-fed and formula-fed infants from 0 to 18 months: the DARLING Study Pediatrics, 89(6 Pt 1), 1035-41 | Intervention/exposure
594 | Dewey, K. G.,Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B. (1993). Breast-fed infants are leaner than formula-fed infants at 1 y of age: the DARLING study Am J Clin Nutr, 57(2), 140-5 | Intervention/exposure
595 | Dewey, K. G.,Heinig, M. J.,Nommsen-Rivers, L. A. (1995). Differences in morbidity between breast-fed and formula-fed infants J Pediatr, 126(5 Pt 1), 696-702 | Intervention/exposure
596 | Dewey, K. G.,Nommsen-Rivers, L. A.,Heinig, M. J.,Cohen, R. J. (2003). Risk factors for suboptimal infant breastfeeding behavior, delayed onset of lactation, and excess neonatal weight loss Pediatrics, 112(3 Pt 1), 607-19 | Intervention/exposure
597 | Dewey, K. G.,Peerson, J. M.,Brown, K. H.,Krebs, N. F.,Michaelsen, K. F.,Persson, L. A.,Salmenpera, L.,Whitehead, R. G.,Yeung, D. L. (1995). Growth of breast-fed infants deviates from current reference data: a pooled analysis of US, Canadian, and European data sets. World Health Organization Working Group on Infant Growth Pediatrics, 96(3 Pt 1), 495-503 | Study design
598 | Dewey, K. G.,Peerson, J. M.,Heinig, M. J.,Nommsen, L. A.,Lonnerdal, B.,Lopez de Romana, G.,de Kanashiro, H. C.,Black, R. E.,Brown, K. H. (1992). Growth patterns of breast-fed infants in affluent (United States) and poor (Peru) communities: implications for timing of complementary feeding Am J Clin Nutr, 56(6), 1012-8 | Study design, Intervention/exposure
599 | Dharmage, S. C.,Rajapaksa, L. C.,Fernando, D. N. (1996). Risk factors of acute lower respiratory tract infections in children under five years of age Southeast Asian J Trop Med Public Health, 27(1), 107-10 | Participant health
600 | Dhillon, S. K.,Davies, W. E.,Hopkins, P. C.,Rose, S. J. (1998). Effects of dietary taurine on auditory function in full-term infants Adv Exp Med Biol, 442(#issue#), 507-14 | Size of study groups
601 | Diaz, S.,Herreros, C.,Aravena, R.,Casado, M. E.,Reyes, M. V.,Schiappacasse, V. (1995). Breast-feeding duration and growth of fully breast-fed infants in a poor urban Chilean population Am J Clin Nutr, 62(2), 371-6 | Intervention/exposure
602 | Diaz, S.,Rodriguez, G.,Marshall, G.,del Pino, G.,Casado, M. E.,Miranda, P.,Schiappacasse, V.,Croxatto, H. B. (1988). Breastfeeding pattern and the duration of lactational amenorrhea in urban Chilean women Contraception, 38(1), 37-51 | Outcome
603 | Diesel, J. C.,Eckhardt, C. L.,Day, N. L.,Brooks, M. M.,Arslanian, S. A.,Bodnar, L. M. (2015). Is gestational weight gain associated with offspring obesity at 36 months? Pediatr Obes, 10(4), 305-10 | Intervention/exposure
604 | Dini, E. L.,Holt, R. D.,Bedi, R. (2000). Caries and its association with infant feeding and oral health-related behaviours in 3-4-year-old Brazilian children Community Dent Oral Epidemiol, 28(4), 241-8 | Study design
605 | Dinsmore, J.,Williams, E.,McCarthy, H.,Coghlan, D. (2011). A pilot study to explore factors affecting faltering growth in children Journal of Human Nutrition & Dietetics, 24(3), 280-281 2p | Size of study groups
606 | Disantis, K. I.,Collins, B. N.,Fisher, J. O.,Davey, A. (2011). Do infants fed directly from the breast have improved appetite regulation and slower growth during early childhood compared with infants fed from a bottle? Int J Behav Nutr Phys Act, 8(#issue#), 89 | Intervention/exposure
607 | Dixon, D. L.,Griggs, K. M.,Forsyth, K. D.,Bersten, A. D. (2010). Lower interleukin-8 levels in airway aspirates from breastfed infants with acute bronchiolitis Pediatr Allergy Immunol, 21(4 Pt 2), e691-6 | Size of study groups, Outcome
608 | Djalalinia, S.,Qorbani, M.,Heshmat, R.,Motlagh, M. E.,Ardalan, G.,Bazyar, N.,Taheri, M.,Asayesh, H.,Kelishadi, R. (2015). Association of Breast Feeding and Birth Weight with Anthropometric Measures and Blood Pressure in Children and Adolescents: The CASPIAN-IV Study Pediatr Neonatol, 56(5), 324-33 | Study design
609 | Dogaru, C. M.,Strippoli, M. P.,Spycher, B. D.,Frey, U.,Beardsmore, C. S.,Silverman, M.,Kuehni, C. E. (2012). Breastfeeding and lung function at school age: does maternal asthma modify the effect? Am J Respir Crit Care Med, 185(8), 874-80 | Outcome
610 | Dogruel, D.,Bingol, G.,Altintas, D. U.,Yilmaz, M.,Kendirli, S. G. (2015). Prevalence of and risk factors for atopic dermatitis: A birth cohort study of infants in southeast Turkey Allergol Immunopathol (Madr), #volume#(#issue#), #Pages# | Intervention/exposure, Size of study groups
611 | Domellof, E.,Timby, N.,Domellof, M.,Lonnerdal, B.,Hernell, O. (2013). Formula feeding supplemented with milk fat globule membranes improves cognitive score in term infants at 12 months Developmental medicine and child neurology, 55(#issue#), 50 | Publication status
612 | Dondi, A.,Tripodi, S.,Panetta, V.,Asero, R.,Businco, A. D.,Bianchi, A.,Carlucci, A.,Ricci, G.,Bellini, F.,Maiello, N.,del Giudice, M. M.,Frediani, T.,Sodano, S.,Dello Iacono, I.,Macri, F.,Massaccesi, V.,Caffarelli, C.,Rinaldi, L.,Patria, M. F.,Varin, E.,Peroni, D.,Chinellato, I.,Chini, L.,Moschese, V.,Lucarelli, S.,Bernardini, R.,Pingitore, G.,Pelosi, U.,Tosca, M.,Paravati, F.,La Grutta, S.,Meglio, P.,Calvani, M.,Plebani, M.,Matricardi, P. M. (2013). Pollen-induced allergic rhinitis in 1360 Italian children: comorbidities and determinants of severity Pediatr Allergy Immunol, 24(8), 742-51 | Study design
613 | Dong, G. H.,Qian, Z. M.,Liu, M. M.,Wang, D.,Ren, W. H.,Bawa, S.,Fu, J.,Wang, J.,Lewis, R.,Zelicoff, A.,Simckes, M.,Trevathan, E. (2013). Breastfeeding as a modifier of the respiratory effects of air pollution in children Epidemiology, 24(3), 387-94 | Study design
614 | Dong, G. H.,Qian, Z. M.,Trevathan, E.,Zeng, X. W.,Vaughn, M. G.,Wang, J.,Zhao, Y.,Liu, Y. Q.,Ren, W. H.,Qin, X. D. (2014). Air pollution associated hypertension and increased blood pressure may be reduced by breastfeeding in Chinese children: the Seven Northeastern Cities Chinese Children’s Study Int J Cardiol, 176(3), 956-61 | Study design
615 | Donma, M. M.,Donma, O. (1997). The influence of feeding patterns on head circumference among Turkish infants during the first 6 months of life Brain Dev, 19(6), 393-7 | Outcome
616 | Donma, M. M.,Donma, O. (1999). Infant feeding and growth: a study on Turkish infants from birth to 6 months Pediatr Int, 41(5), 542-8 | Intervention/exposure
617 | Donohue, L. (1994). Baby Friendly Hospitals in China Aust J Adv Nurs, 12(2), 7 | Study design
618 | Doran, E. (1983). Breast is best for lightweights Nurs Mirror, 156(12), 46-7 | Participant health
619 | Dorea, J. G. (1997). Zinc in urban infants and children from Brasilia Arch Latinoam Nutr, 47(2 Suppl 1), 39-40 | Study design
620 | Dorea, J. G.,Marques, R. C.,Isejima, C. (2012). Neurodevelopment of Amazonian infants: antenatal and postnatal exposure to methyl- and ethylmercury J Biomed Biotechnol, 2012(#issue#), 132876 | Study design, Intervention/exposure
621 | Dotan, I.,Alper, A.,Rachmilewitz, D.,Israeli, E.,Odes, S.,Chermesh, I.,Naftali, T.,Fraser, G.,Shitrit, A. B.,Peles, V.,Reif, S. (2013). Maternal inflammatory bowel disease has short and long-term effects on the health of their offspring: a multicenter study in Israel J Crohns Colitis, 7(7), 542-50 | Intervention/exposure, Outcome
622 | Douglas, R. M.,Woodward, A.,Miles, H.,Buetow, S.,Morris, D. (1994). A prospective study of proneness to acute respiratory illness in the first two years of life Int J Epidemiol, 23(4), 818-26 | Outcome
623 | Doumid Borges Pretto, A.,Correa Kaufmann, C.,Ferreira Dutra, G.,Pinto Albernaz, E. (2015). Prevalence of factors related to the bone mass formation of children from a cohort in Southern Brazil Nutr Hosp, 31(3), 1122-8 | Intervention/exposure
624 | Draaisma, E.,Garcia-Marcos, L.,Mallol, J.,Sole, D.,Perez-Fernandez, V.,Brand, P. L. (2015). A multinational study to compare prevalence of atopic dermatitis in the first year of life Pediatr Allergy Immunol, 26(4), 359-66 | Study design, Outcome
625 | Dratva, J.,Merten, S.,Ackermann-Liebrich, U. (2006). Vitamin D supplementation in Swiss infants Swiss Med Wkly, 136(29-30), 473-81 | Study design, Outcome
626 | Drewett, R. F.,Amatayakul, K. (1999). Energy intake, appetite and body mass in infancy Early Hum Dev, 56(1), 75-82 | Intervention/exposure
627 | Drewett, R.,Amatayakul, K.,Chiowanich, P.,Tansuhaj, A.,Ruckphaopunt, S.,Wongsawasdii, L.,Baum, D.,Imong, S.,Jackson, D.,Woolridge, M. (1991). The Chiang Mai lactation project: study design and implementation Paediatr Perinat Epidemiol, 5(3), 347-60 | Intervention/exposure
628 | Drover, J.,Hoffman, D. R.,Castaneda, Y. S.,Morale, S. E.,Birch, E. E. (2009). Three randomized controlled trials of early long-chain polyunsaturated Fatty Acid supplementation on means-end problem solving in 9-month-olds Child Dev, 80(5), 1376-84 | Intervention/exposure
629 | Du, Y.,Ellert, U.,Lampert, T.,Mensink, G. B.,Schlaud, M. (2012). Association of breastfeeding and exposure to maternal smoking during pregnancy with children’s general health status later in childhood Breastfeed Med, 7(6), 504-13 | Study design, Outcome
630 | Dubakiene, R.,Rudzeviciene, O.,Butiene, I.,Sezaite, I.,Petronyte, M.,Vaicekauskaite, D.,Zvirbliene, A. (2012). Studies on early allergic sensitization in the Lithuanian birth cohort ScientificWorldJournal, 2012(#issue#), 909524 | Intervention/exposure
631 | Dube, K.,Schwartz, J.,Mueller, M. J.,Kalhoff, H.,Kersting, M. (2010). Iron intake and iron status in breastfed infants during the first year of life Clin Nutr, 29(6), 773-8 | Size of study groups
632 | Dubois, L.,Girard, M. (2006). Early determinants of overweight at 4.5 years in a population-based longitudinal study Int J Obes (Lond), 30(4), 610-7 | Intervention/exposure
633 | Duffy, L. C.,Byers, T. E.,Riepenhoff-Talty, M.,La Scolea, L. J.,Zielezny, M.,Ogra, P. L. (1986). The effects of infant feeding on rotavirus-induced gastroenteritis: a prospective study Am J Public Health, 76(3), 259-63 | Outcome
634 | Duffy, L. C.,Faden, H.,Wasielewski, R.,Wolf, J.,Krystofik, D. (1997). Exclusive breastfeeding protects against bacterial colonization and day care exposure to otitis media Pediatrics, 100(4), E7 | Outcome
635 | Duffy, L. C.,Riepenhoff-Talty, M.,Byers, T. E.,La Scolea, L. J.,Zielezny, M. A.,Dryja, D. M.,Ogra, P. L. (1986). Modulation of rotavirus enteritis during breast-feeding. Implications on alterations in the intestinal bacterial flora Am J Dis Child, 140(11), 1164-8 | Outcome
636 | Dugdale, A. E. (1980). Infant feeding, growth and mortality: a 20-year study of an Australian Aboriginal community Med J Aust, 2(7), 380-5 | Outcome
637 | Duijts, L.,Jaddoe, V. W.,Hofman, A.,Moll, H. A. (2010). Prolonged and exclusive breastfeeding reduces the risk of infectious diseases in infancy Pediatrics, 126(1), e18-25 | Outcome
638 | Dumrongwongsiri, O.,Suthutvoravut, U.,Chatvutinun, S.,Phoonlabdacha, P.,Sangcakul, A.,Siripinyanond, A.,Thiengmanee, U.,Chongviriyaphan, N. (2015). Maternal zinc status is associated with breast milk zinc concentration and zinc status in breastfed infants aged 4-6 months Asia Pac J Clin Nutr, 24(2), 273-80 | Study design
639 | Duncan, B.,Ey, J.,Holberg, C. J.,Wright, A. L.,Martinez, F. D.,Taussig, L. M. (1993). Exclusive breast-feeding for at least 4 months protects against otitis media Pediatrics, 91(5), 867-72 | Outcome
640 | Dunlop, A. L.,Reichrtova, E.,Palcovicova, L.,Ciznar, P.,Adamcakova-Dodd, A.,Smith, S. J.,McNabb, S. J. (2006). Environmental and dietary risk factors for infantile atopic eczema among a Slovak birth cohort Pediatr Allergy Immunol, 17(2), 103-11 | Study design
641 | Dunne, A. (2012). Early infant nutrition: the importance of getting it right Br J Nurs, 21(7), 390 | Study design
642 | Dunne, A. (2012). Nutrition in infancy: achieving nutrition needs for new mothers and children Br J Community Nurs, Suppl(#issue#), S22 | Study design
643 | Dunson, D. B.,Chulada, P.,Arbes, S. J., Jr. (2003). Bayesian modeling of time-varying and waning exposure effects Biometrics, 59(1), 83-91 | Study design
644 | Dunstan, J. A.,Mitoulas, L. R.,Dixon, G.,Doherty, D. A.,Hartmann, P. E.,Simmer, K.,Prescott, S. L. (2007). The effects of fish oil supplementation in pregnancy on breast milk fatty acid composition over the course of lactation: a randomized controlled trial Pediatr Res, 62(6), 689-94 | Intervention/exposure, Outcome
645 | Durmu, B.,Ay, L.,Duijts, L.,Moll, H. A.,Hokken-Koelega, A. C. S.,Raat, H.,Hofman, A.,Steegers, E. A. P.,Jaddoe, V. W. V. (2012). Infant diet and subcutaneous fat mass in early childhood: The Generation R Study European Journal of Clinical Nutrition, 66(2), 253-260 | Outcome
646 | Durmus, B.,Ay, L.,Hokken-Koelega, A. C.,Raat, H.,Hofman, A.,Steegers, E. A.,Jaddoe, V. W. (2011). Maternal smoking during pregnancy and subcutaneous fat mass in early childhood. The Generation R Study Eur J Epidemiol, 26(4), 295-304 | Intervention/exposure
647 | Durmus, B.,Heppe, D. H.,Gishti, O.,Manniesing, R.,Abrahamse-Berkeveld, M.,van der Beek, E. M.,Hofman, A.,Duijts, L.,Gaillard, R.,Jaddoe, V. W. (2014). General and abdominal fat outcomes in school-age children associated with infant breastfeeding patterns Am J Clin Nutr, 99(6), 1351-8 | Outcome
648 | Durmus, B.,van Rossem, L.,Duijts, L.,Arends, L. R.,Raat, H.,Moll, H. A.,Hofman, A.,Steegers, E. A.,Jaddoe, V. W. (2011). Breast-feeding and growth in children until the age of 3 years: the Generation R Study Br J Nutr, 105(11), 1704-11 | Outcome
649 | Dutta, P.,Lahiri, M.,Sen, D.,Pal, S. C. (1991). Prospective hospital based study on persistent diarrhoea Gut, 32(7), 787-90 | Country
650 | Dwyer, T.,Ponsonby, A. L. (1995). SIDS epidemiology and incidence Pediatr Ann, 24(7), 350-2, 354-6 | Study design
651 | Eaton-Evans, J.,Dugdale, A. E. (1987). Effects of feeding and social factors on diarrhoea and vomiting in infants Arch Dis Child, 62(5), 445-8 | Outcome
652 | Ebina, S.,Kashiwakura, I. (2013). Relationship between feeding modes and infant weight gain in the first month of life Exp Ther Med, 5(1), 28-32 | Outcome
653 | Eckhardt, C. L.,Rivera, J.,Adair, L. S.,Martorell, R. (2001). Full breast-feeding for at least four months has differential effects on growth before and after six months of age among children in a Mexican community J Nutr, 131(9), 2304-9 | Intervention/exposure
654 | Ecord, J. S. (2003). Critical connections. Study finds full breastfeeding for 6 months boosts infant’s resistance to respiratory illnesses Advances in Neonatal Care (Elsevier Science), 3(1), 2-2 1p | Study design
655 | Edwards, C. A.,Parrett, A. M.,Balmer, S. E.,Wharton, B. A. (1994). Faecal short chain fatty acids in breast-fed and formula-fed babies Acta Paediatr, 83(5), 459-62 | Size of study groups, Outcome
656 | Eglinton, T. W.,Roberts, R.,Pearson, J.,Barclay, M.,Merriman, T. R.,Frizelle, F. A.,Gearry, R. B. (2012). Clinical and genetic risk factors for perianal Crohn’s disease in a population-based cohort Am J Gastroenterol, 107(4), 589-96 | Outcome
657 | Eickmann, S. H.,de Lira, P. I.,Lima Mde, C.,Coutinho, S. B.,Teixeira Mde, L.,Ashworth, A. (2007). Breast feeding and mental and motor development at 12 months in a low-income population in northeast Brazil Paediatr Perinat Epidemiol, 21(2), 129-37 | Size of study groups, Intervention/exposure
658 | Eidelman, A. I. (2013). Breastfeeding mitigates a disaster Breastfeed Med, 8(3), 344-5 | Study design
659 | Eiger, M. S.,Rausen, A. R.,Silverio, J. (1984). Breast-vs. bottle-feeding. A study of morbidity in upper middle class infants Clin Pediatr (Phila), 23(9), 492-5 | Size of study groups
660 | Ejlerskov, K. T.,Christensen, L. B.,Ritz, C.,Jensen, S. M.,Molgaard, C.,Michaelsen, K. F. (2015). The impact of early growth patterns and infant feeding on body composition at 3 years of age Br J Nutr, 114(2), 316-27 | Intervention/exposure
661 | Ek, J.,Magnus, E. (1982). Plasma and red cell folate values and folate requirements in formula-fed term infants J Pediatr, 100(5), 738-44 | Size of study groups
662 | Ekstrom, A.,Abrahamsson, H.,Eriksson, R. M.,Martensson, B. L. (2014). Women’s use of nipple shields-Their influence on breastfeeding duration after a process-oriented education for health professionals Breastfeed Med, 9(9), 458-66 | Intervention/exposure
663 | Elborn, G.,Kerr, M. M. (1982). Acceptability trial of “Milumil” artificial milk for infant feeding Midwives Chron, 95(1133), 210-1 | Intervention/exposure
664 | Eldeirawi, K.,McConnell, R.,Furner, S.,Freels, S.,Stayner, L.,Hernandez, E.,Amoruso, L.,Torres, S.,Persky, V. W. (2009). Associations of doctor-diagnosed asthma with immigration status, age at immigration, and length of residence in the United States in a sample of Mexican American School Children in Chicago J Asthma, 46(8), 796-802 | Study design
665 | El-Gilany, A. H.,El-Wehady, A. (2007). Maternal work and infant health in Al-Hassa, Saudi Arabia Paediatrics ME, 12(4), 100-105 | Study design
666 | Elidrissy, A. T.,Sedrani, S. H.,Lawson, D. E. (1984). Vitamin D deficiency in mothers of rachitic infants Calcif Tissue Int, 36(3), 266-8 | Study design, Intervention/exposure
667 | Elliott, K. G.,Kjolhede, C. L.,Gournis, E.,Rasmussen, K. M. (1997). Duration of breastfeeding associated with obesity during adolescence Obes Res, 5(6), 538-41 | Outcome
668 | Elliott, L.,Henderson, J.,Northstone, K.,Chiu, G. Y.,Dunson, D.,London, S. J. (2008). Prospective study of breast-feeding in relation to wheeze, atopy, and bronchial hyperresponsiveness in the Avon Longitudinal Study of Parents and Children (ALSPAC) J Allergy Clin Immunol, 122(1), 49-54, 54 e1-3 | Outcome
669 | Elwood, P. C.,Pickering, J.,Gallacher, J. E.,Hughes, J.,Davies, D. (2005). Long term effect of breast feeding: cognitive function in the Caerphilly cohort J Epidemiol Community Health, 59(2), 130-3 | Outcome
670 | Emamghorashi, F.,Heydari, S. T. (2007). Growth of infants in relation to type of feeding in Jahrom, Islamic Republic of Iran East Mediterr Health J, 13(4), 846-54 | Outcome
671 | Emilsson, L.,Magnus, M. C.,Stordal, K. (2015). Perinatal risk factors for development of celiac disease in children, based on the prospective Norwegian Mother and Child Cohort Study Clin Gastroenterol Hepatol, 13(5), 921-7 | Intervention/exposure
672 | Emmett, P. M.,Jones, L. R. (2014). Diet and growth in infancy: relationship to socioeconomic background and to health and development in the Avon Longitudinal Study of Parents and Children Nutr Rev, 72(8), 483-506 | Study design
673 | Emond, A.,Drewett, R.,Blair, P.,Emmett, P. (2007). Postnatal factors associated with failure to thrive in term infants in the Avon Longitudinal Study of Parents and Children Arch Dis Child, 92(2), 115-9 | Outcome
674 | Emond, A.,Pollock, J.,Da Costa, N.,Maranhao, T.,Macedo, A. (2002). The effectiveness of community-based interventions to improve maternal and infant health in the Northeast of Brazil Rev Panam Salud Publica, 12(2), 101-10 | Study design, Intervention/exposure
675 | Endesfelder, D.,zu Castell, W.,Ardissone, A.,Davis-Richardson, A. G.,Achenbach, P.,Hagen, M.,Pflueger, M.,Gano, K. A.,Fagen, J. R.,Drew, J. C.,Brown, C. T.,Kolaczkowski, B.,Atkinson, M.,Schatz, D.,Bonifacio, E.,Triplett, E. W.,Ziegler, A. G. (2014). Compromised gut microbiota networks in children with anti-islet cell autoimmunity Diabetes, 63(6), 2006-14 | Intervention/exposure, Outcome
676 | Engel, J.,Anteunis, L.,Volovics, A.,Hendriks, J.,Marres, E. (1999). Risk factors of otitis media with effusion during infancy Int J Pediatr Otorhinolaryngol, 48(3), 239-49 | Outcome
677 | Eriksen, H. L.,Kesmodel, U. S.,Underbjerg, M.,Kilburn, T. R.,Bertrand, J.,Mortensen, E. L. (2013). Predictors of intelligence at the age of 5: family, pregnancy and birth characteristics, postnatal influences, and postnatal growth PLoS One, 8(11), e79200 | Study design
678 | Eriksson, J.,Forsen, T.,Osmond, C.,Barker, D. (2003). Obesity from cradle to grave Int J Obes Relat Metab Disord, 27(6), 722-7 | Intervention/exposure
679 | Eriksson, M.,Forsgren, M.,Sjoberg, S.,von Sydow, M.,Wolontis, S. (1983). Respiratory syncytial virus infection in young hospitalized children. Identification of risk patients and prevention of nosocomial spread by rapid diagnosis Acta Paediatr Scand, 72(1), 47-51 | Study design, Participant health
680 | Ernst, E. (2001). Probiotics may prevent atopic disease Focus on Alternative & Complementary Therapies, 6(3), 204-205 2p | Study design
681 | Eronat, N.,Eden, E. (1992). A comparative study of some influencing factors of rampant or nursing caries in preschool children J Clin Pediatr Dent, 16(4), 275-9 | Study design, Intervention/exposure
682 | Escribano, J.,Luque, V.,Ferre, N.,Mendez-Riera, G.,Koletzko, B.,Grote, V.,Demmelmair, H.,Bluck, L.,Wright, A.,Closa-Monasterolo, R. (2012). Effect of protein intake and weight gain velocity on body fat mass at 6 months of age: the EU Childhood Obesity Programme Int J Obes (Lond), 36(4), 548-53 | Intervention/exposure, Size of study groups
683 | Esfarjani, F.,Azar, M. R.,Gafarpour, M. (2001). IDDM and early exposure of infant to cow’s milk and solid food Indian J Pediatr, 68(2), 107-10 | Outcome
684 | Eskenazi, B.,Marks, A. R.,Bradman, A.,Fenster, L.,Johnson, C.,Barr, D. B.,Jewell, N. P. (2006). In utero exposure to dichlorodiphenyltrichloroethane (DDT) and dichlorodiphenyldichloroethylene (DDE) and neurodevelopment among young Mexican American children Pediatrics, 118(1), 233-41 | Study design
685 | Esmail, A.,Lambert, P. C.,Jones, D. R.,Mitchell, E. A. (1995). Prevalence of risk factors for sudden infant death syndrome in south east England before the 1991 national ‘Back to Sleep’ health education campaign J Public Health Med, 17(3), 282-9 | Study design
686 | Estevez-Gonzalez, M. D.,Santana Del Pino, A.,Henriquez-Sanchez, P.,Pena-Quintana, L.,Saavedra-Santana, P. (2015). Breastfeeding during the first six months of life, adiposity rebound and overweight/obesity at eight years of age Int J Obes (Lond), #volume#(#issue#), #Pages# | Outcome
687 | Ethelberg, S.,Olesen, B.,Neimann, J.,Schiellerup, P.,Helms, M.,Jensen, C.,Böttiger, B.,Olsen, K. E. P.,Scheutz, F.,Gerner-Smidt, P.,Mølbak, K. (2006). Risk factors for diarrhea among children in an industrialized country Epidemiology, 17(1), 24-30 | Study design, Intervention/exposure
688 | Etiler, N.,Velipasaoglu, S.,Aktekin, M. (2002). Incidence of acute respiratory infections and the relationship with some factors in infancy in Antalya, Turkey Pediatr Int, 44(1), 64-9 | Outcome
689 | Etiler, N.,Velipasaoglu, S.,Aktekin, M. (2004). Risk factors for overall and persistent diarrhoea in infancy in Antalya, Turkey: a cohort study Public Health, 118(1), 62-9 | Outcome
690 | Etling, N.,Padovani, E.,Gehin-Fouque, F.,Tato, L. (1983). Iodine and thyroid hormone levels in serum and urine of full term newborn infants Helv Paediatr Acta, 38(2), 117-22 | Size of study groups, Intervention/exposure
691 | Evelein, A. M.,Geerts, C. C.,Visseren, F. L.,Bots, M. L.,van der Ent, C. K.,Grobbee, D. E.,Uiterwaal, C. S. (2011). The association between breastfeeding and the cardiovascular system in early childhood Am J Clin Nutr, 93(4), 712-8 | Outcome
692 | Evenhouse, E.,Reilly, S. (2005). Improved estimates of the benefits of breastfeeding using sibling comparisons to reduce selection bias Health Serv Res, 40(6 Pt 1), 1781-802 | Outcome
693 | Exl, B. M.,Deland, U.,Secretin, M. C.,Preysch, U.,Wall, M.,Shmerling, D. H. (2000). Improved general health status in an unselected infant population following an allergen-reduced dietary intervention programme: The ZUFF-STUDY-PROGRAMME - Part II: Infant growth and health status to age 6 months European Journal of Nutrition, 39(4), 145-156 | Study design, Outcome
694 | Exl, B. M.,Deland, U.,Wall, M.,Preysch, U.,Secretin, M. C.,Shmerling, D. H. (1998). Zug-Frauenfeld nutritional survey (‘Zuff Study’): Allergen-reduced nutrition in a normal infant population and its health-related effects: Results at the age of six months Nutrition research (New York, N.Y.), 18(8), 1443-62 | Study design
695 | Fagrell, T. G.,Ludvigsson, J.,Ullbro, C.,Lundin, S. A.,Koch, G. (2011). Aetiology of severe demarcated enamel opacities--an evaluation based on prospective medical and social data from 17,000 children Swed Dent J, 35(2), 57-67 | Outcome
696 | Fall, C. H.,Barker, D. J.,Osmond, C.,Winter, P. D.,Clark, P. M.,Hales, C. N. (1992). Relation of infant feeding to adult serum cholesterol concentration and death from ischaemic heart disease BMJ, 304(6830), 801-5 | Outcome
697 | Fall, C. H.,Borja, J. B.,Osmond, C.,Richter, L.,Bhargava, S. K.,Martorell, R.,Stein, A. D.,Barros, F. C.,Victora, C. G. (2011). Infant-feeding patterns and cardiovascular risk factors in young adulthood: data from five cohorts in low- and middle-income countries Int J Epidemiol, 40(1), 47-62 | Study design, Redundant data with another study
698 | Fallot, M. E.,Boyd, J. L., 3rd,Oski, F. A. (1980). Breast-feeding reduces incidence of hospital admissions for infection in infants Pediatrics, 65(6), 1121-4 | Study design, Size of study groups
699 | Falth-Magnusson, K.,Franzen, L.,Jansson, G.,Laurin, P.,Stenhammar, L. (1996). Infant feeding history shows distinct differences between Swedish celiac and reference children Pediatr Allergy Immunol, 7(1), 1-5 | Outcome
700 | Falth-Magnusson, K.,Kjellman, N. I. (1987). Development of atopic disease in babies whose mothers were receiving exclusion diet during pregnancy--a randomized study J Allergy Clin Immunol, 80(6), 868-75 | Intervention/exposure
701 | Farham, B. (2006). Rethink formula feeding South African medical journal, 96(10), 1054 | Study design
702 | Farooqi, I. S.,Hopkin, J. M. (1998). Early childhood infection and atopic disorder Thorax, 53(11), 927-32 | Intervention/exposure
703 | Farris, R. P.,Frank, G. C.,Webber, L. S.,Srinivasan, S. R.,Berenson, G. S. (1982). Influence of milk source on serum lipids and lipoproteins during the first year of life, Bogalusa heart study Am J Clin Nutr, 35(1), 42-9 | Size of study groups, Intervention/exposure
704 | Fawcett JN (1981). Feeding from birth to 18 months Nursing (Lond), #volume#(#issue#), 956-8 | Study design
705 | Fawzi, W. W.,Forman, M. R.,Levy, A.,Graubard, B. I.,Naggan, L.,Berendes, H. W. (1997). Maternal anthropometry and infant feeding practices in Israel in relation to growth in infancy: the North African Infant Feeding Study Am J Clin Nutr, 65(6), 1731-7 | Outcome
706 | Fawzi, W. W.,Herrera, M. G.,Nestel, P.,el Amin, A.,Mohamed, K. A. (1998). A longitudinal study of prolonged breastfeeding in relation to child undernutrition Int J Epidemiol, 27(2), 255-60 | Country
707 | Feig, D. S.,Lipscombe, L. L.,Tomlinson, G.,Blumer, I. (2011). Breastfeeding predicts the risk of childhood obesity in a multi-ethnic cohort of women with diabetes J Matern Fetal Neonatal Med, 24(3), 511-5 | Study design
708 | Feigal, R. J. (1985). Common oral diseases of children Pediatr Ann, 14(2), 133-8 | Study design
709 | Fein, S. B.,Grummer-Strawn, L. M.,Raju, T. N. (2008). Infant feeding and care practices in the United States: results from the Infant Feeding Practices Study II Pediatrics, 122 Suppl 2(#issue#), S25-7 | Study design
710 | Feldens, C. A.,Giugliani, E. R.,Duncan, B. B.,Drachler Mde, L.,Vitolo, M. R. (2010). Long-term effectiveness of a nutritional program in reducing early childhood caries: a randomized trial Community Dent Oral Epidemiol, 38(4), 324-32 | Outcome
711 | Feldens, C. A.,Giugliani, E. R.,Vigo, A.,Vitolo, M. R. (2010). Early feeding practices and severe early childhood caries in four-year-old children from southern Brazil: a birth cohort study Caries Res, 44(5), 445-52 | Outcome
712 | Feldens, C. A.,Kramer, P. F.,Feldens, E. G.,Pacheco, L. M.,Vitolo, M. R. (2014). Socioeconomic, behavioral, and anthropometric risk factors for traumatic dental injuries in childhood: a cohort study Int J Paediatr Dent, 24(3), 234-43 | Outcome
713 | Feldens, C. A.,Vitolo, M. R.,Drachler Mde, L. (2007). A randomized trial of the effectiveness of home visits in preventing early childhood caries Community Dent Oral Epidemiol, 35(3), 215-23 | Outcome
714 | Fenger-Gron J, Fenger-Gron M, Blunck CH, Schonemann-Rigel H, Wielandt HB. (2015). Low breastfeeding rates and body mass index in Danish children of women with gestational diabetes mellitus International Breastfeeding Journal, 10(1), 1-12 | Intervention/exposure
715 | Ferguson, A. E.,Tappin, D. M.,Girdwood, R. W. A.,Kennedy, R.,Cockburn, F. (1994). Breast feeding in Scotland British Medical Journal, 308(6932), 824-825 | Study design, Outcome
716 | Fergusson, D. M.,Beautrais, A. L.,Silva, P. A. (1982). Breast-feeding and cognitive development in the first seven years of life Soc Sci Med, 16(19), 1705-8 | Outcome
717 | Fergusson, D. M.,Horwood, L. J. (1994). Early solid food diet and eczema in childhood: a 10-year longitudinal study Pediatr Allergy Immunol, 5(6 Suppl), 44-7 | Intervention/exposure
718 | Fergusson, D. M.,Horwood, L. J.,Beautrais, A. L.,Shannon, F. T.,Taylor, B. (1981). Eczema and infant diet Clin Allergy, 11(4), 325-31 | Intervention/exposure
719 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T. (1982). Risk factors in childhood eczema J Epidemiol Community Health, 36(2), 118-22 | Intervention/exposure
720 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T. (1983). Asthma and infant diet Arch Dis Child, 58(1), 48-51 | Size of study groups, Intervention/exposure
721 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T. (1987). Breastfeeding and subsequent social adjustment in six- to eight-year-old children J Child Psychol Psychiatry, 28(3), 379-86 | Outcome
722 | Fergusson, D. M.,Horwood, L. J.,Shannon, F. T.,Taylor, B. (1981). Breast-feeding, gastrointestinal and lower respiratory illness in the first two years Aust Paediatr J, 17(3), 191-5 | Outcome
723 | Fergusson, D. M.,McLeod, G. F.,Horwood, L. J. (2014). Breast feeding, infant growth, and body mass index at 30 and 35 years Paediatr Perinat Epidemiol, 28(6), 545-52 | Outcome
724 | Fergusson, D. M.,Woodward, L. J. (1999). Breast feeding and later psychosocial adjustment Paediatr Perinat Epidemiol, 13(2), 144-57 | Outcome
725 | Ferris, A. G.,Laus, M. J.,Hosmer, D. W.,Beal, V. A. (1980). The effect of diet on weight gain in infancy Am J Clin Nutr, 33(12), 2635-42 | Size of study groups, Intervention/exposure
726 | Fewtrell, M. S.,Kennedy, K.,Murgatroyd, P. R.,Williams, J. E.,Chomtho, S.,Lucas, A. (2013). Breast-feeding and formula feeding in healthy term infants and bone health at age 10 years Br J Nutr, 110(6), 1061-7 | Size of study groups
727 | Field, C. J.,Van Aerde, J. E.,Robinson, L. E.,Clandinin, M. T. (2008). Feeding a formula supplemented with long chain polyunsaturated fatty acids modifies the “ex vivo” cytokine responses to food proteins in infants at low risk for allergy Pediatr Res, 64(4), 411-7 | Size of study groups
728 | Field, S. S. (2014). Interaction of genes and nutritional factors in the etiology of autism and attention deficit/hyperactivity disorders: a case control study Med Hypotheses, 82(6), 654-61 | Outcome
729 | Fildes, A.,van Jaarsveld, C. H.,Llewellyn, C.,Wardle, J.,Fisher, A. (2015). Parental control over feeding in infancy. Influence of infant weight, appetite and feeding method Appetite, 91(#issue#), 101-6 | Outcome
730 | Fildes, V. (1980). Weaning: on the bottle again Nurs Mirror, 151(24), 18-21 | Study design
731 | Findeisen, M.,Vennemann, M.,Brinkmann, B.,Ortmann, C.,Rose, I.,Kopcke, W.,Jorch, G.,Bajanowski, T. (2004). German study on sudden infant death (GeSID): design, epidemiological and pathological profile Int J Legal Med, 118(3), 163-9 | Outcome
732 | Firer, M. A.,Hosking, C. S.,Hill, D. J. (1981). Effect of antigen load on development of milk antibodies in infants allergic to milk Br Med J (Clin Res Ed), 283(6293), 693-6 | Size of study groups
733 | Fisher C (1985). Breastfeeding. Two. Feeding the relationship Nurs Times, 81(#issue#), 51 | Study design
734 | Fisher SE,Markowitz J,Lifshitz F (1984). Food intolerance in childhood Compr Ther, 10(#issue#), 5-11 | Study design
735 | Fisk, C. M.,Crozier, S. R.,Inskip, H. M.,Godfrey, K. M.,Cooper, C.,Roberts, G. C.,Robinson, S. M. (2011). Breastfeeding and reported morbidity during infancy: findings from the Southampton Women’s Survey Matern Child Nutr, 7(1), 61-70 | Outcome
736 | Fitzgerald, S.,Kearney, M.,Mahony, M.,O’Halloran, E. T.,Barry, R. G. (1982). Gastroenteritis 1972-1978 Ir Med J, 75(5), 155-7 | Study design
737 | Flaherman, V. J.,Bokser, S.,Newman, T. B. (2010). First-day newborn weight loss predicts in-hospital weight nadir for breastfeeding infants Breastfeed Med, 5(4), 165-8 | Intervention/exposure
738 | Flaherman, V. J.,Fuentes-Afflick, E. (2014). Social and public health perspectives of promotion of breastfeeding JAMA Pediatr, 168(10), 877-8 | Study design
739 | Flaherman, V. J.,Kuzniewicz, M. W.,Li, S.,Walsh, E.,McCulloch, C. E.,Newman, T. B. (2013). First-day weight loss predicts eventual weight nadir for breastfeeding newborns Arch Dis Child Fetal Neonatal Ed, 98(6), F488-92 | Intervention/exposure, Outcome
740 | Flaherman, V.,Aby, J.,Burgos, A.,Lee, K.,Cabana, M.,Newman, T. (2012). Randomized Trial of Early Limited Formula To Reduce Formula Use at 1 Week and Promote Breastfeeding at 3 Months in Infants with High Early Weight Loss Pediatric Academic Societies Annual Meeting, #volume#(#issue#), #Pages# | Publication status
741 | Fleddermann, M.,Demmelmair, H.,Grote, V.,Nikolic, T.,Koletzko, B. (2013). A protein reduced, alpha-lactalbumin and LC-PUFA containing infant formula enables an adequate growth in infants and influences the energetic efficiency for growth: A randomized controlled trial Clinical nutrition (Edinburgh, Scotland), 32(#issue#), S16 | Publication status
742 | Fleming, P. J.,Blair, P. S.,Bacon, C.,Bensley, D.,Smith, I.,Taylor, E.,Berry, J.,Golding, J.,Tripp, J. (1996). Environment of infants during sleep and risk of the sudden infant death syndrome: results of 1993-5 case-control study for confidential inquiry into stillbirths and deaths in infancy. Confidential Enquiry into Stillbirths and Deaths Regional Coordinators and Researchers BMJ, 313(7051), 191-5 | Outcome
743 | Fleming, P. J.,Blair, P. S.,Ward Platt, M.,Tripp, J.,Smith, I. J. (2003). Sudden infant death syndrome and social deprivation: assessing epidemiological factors after post-matching for deprivation Paediatr Perinat Epidemiol, 17(3), 272-80 | Outcome
744 | Fleming, T. (2008). Breast is best to avoid obesity: study Pharmacy News, #volume#(#issue#), 4-4 1p | Publication status
745 | Flohr, C.,Nagel, G.,Weinmayr, G.,Kleiner, A.,Strachan, D. P.,Williams, H. C. (2011). Lack of evidence for a protective effect of prolonged breastfeeding on childhood eczema: lessons from the International Study of Asthma and Allergies in Childhood (ISAAC) Phase Two Br J Dermatol, 165(6), 1280-9 | Study design
746 | Flohr, C.,Perkin, M.,Logan, K.,Marrs, T.,Radulovic, S.,Campbell, L. E.,Maccallum, S. F.,McLean, W. H.,Lack, G. (2014). Atopic dermatitis and disease severity are the main risk factors for food sensitization in exclusively breastfed infants J Invest Dermatol, 134(2), 345-50 | Intervention/exposure
747 | Flores, M. S.,Fairchok, M. P. (2004). The relationship of breastfeeding to antimicrobial exposure in the first year of life Clin Pediatr (Phila), 43(7), 631-6 | Outcome
748 | Flores, M.,Pasquel, M. R.,Maulen, I.,Rivera, J. (2005). Exclusive breastfeeding in 3 rural localities in Mexico J Hum Lact, 21(3), 276-83 | Study design, Intervention/exposure
749 | Floret, D.,Lina, B.,Pinchinat, S.,Billaud, G.,Ait-Belghiti, F.,Largeron, N.,Bellemin, B.,Trang, C. N.,Fau, C.,Gaspard, C.,Mamoux, V.,Marcelon, L. (2006). Epidemiology and burden of rotavirus diarrhea in day care centers in Lyon, France Eur J Pediatr, 165(12), 905-6 | Study design, Intervention/exposure
750 | Florey, C. D.,Leech, A. M.,Blackhall, A. (1995). Infant feeding and mental and motor development at 18 months of age in first born singletons Int J Epidemiol, 24 Suppl 1(#issue#), S21-6 | Outcome
751 | Florez, C. E.,Hogan, D. P. (1990). Women’s status and infant mortality in rural Colombia Soc Biol, 37(3-4), 188-203 | Study design, Intervention/exposure
752 | Fogaca, H. R.,Marson, F. A.,Toro, A. A.,Sole, D.,Ribeiro, J. D. (2014). Epidemiological aspects of and risk factors for wheezing in the first year of life J Bras Pneumol, 40(6), 617-25 | Study design
753 | Fokkema MR,Smit EN,Martini IA,Woltil HA,Boersma ER,Muskiet FA (2002). Assessment of essential fatty acid and omega3-fatty acid status by measurement of erythrocyte 20:3omega9 (Mead acid), 22:5omega6/20:4omega6 and 22:5omega6/22:6omega3 Prostaglandins Leukot Essent Fatty Acids, 67(#issue#), 345-56 | Intervention/exposure
754 | Foley, S.,Quinn, S.,Jones, G. (2009). Tracking of bone mass from childhood to adolescence and factors that predict deviation from tracking Bone, 44(5), 752-7 | Outcome
755 | Folic, N.,Folic, M.,Markovic, S.,Andjelkovic, M.,Jankovic, S. (2015). Risk factors for the development of metabolic syndrome in obese children and adolescents Srp Arh Celok Lek, 143(3-4), 146-52 | Study design, Size of study groups
756 | Fomon, S. J. (1980). Factors influencing food consumption in the human infant Int J Obes, 4(4), 348-50 | Study design
757 | Fomon, S. J. (2004). Assessment of growth of formula-fed infants: evolutionary considerations Pediatrics, 113(2), 389-93 | Study design
758 | Fomon, S. J.,Rogers, R. R.,Ziegler, E. E.,Nelson, S. E.,Thomas, L. N. (1984). Indices of fatness and serum cholesterol at age eight years in relation to feeding and growth during early infancy Pediatr Res, 18(12), 1233-8 | Intervention/exposure
759 | Fomon, S. J.,Ziegler, E. E.,Nelson, S. E. (1993). Erythrocyte incorporation of ingested 58Fe by 56-day-old breast-fed and formula-fed infants Pediatr Res, 33(6), 573-6 | Size of study groups
760 | Fomon, S. J.,Ziegler, E. E.,Nelson, S. E.,Rogers, R. R.,Frantz, J. A. (1999). Infant formula with protein-energy ratio of 1.7 g/100 kcal is adequate but may not be safe J Pediatr Gastroenterol Nutr, 28(5), 495-501 | Outcome
761 | Fonseca, A. L.,Albernaz, E. P.,Kaufmann, C. C.,Neves, I. H.,Figueiredo, V. L. (2013). Impact of breastfeeding on the intelligence quotient of eight-year-old children J Pediatr (Rio J), 89(4), 346-53 | Intervention/exposure
762 | Fonseca, M. J.,Moreira, A.,Moreira, P.,Delgado, L.,Teixeira, V.,Padrão, P. (2010). Duration of breastfeeding and the risk of childhood asthma in children living in urban areas Journal of Investigational Allergology and Clinical Immunology, 20(4), 357-358 | Study design
763 | Fonseca, M. J.,Severo, M.,Barros, H.,Santos, A. C. (2014). Determinants of weight changes during the first 96 hours of life in full-term newborns Birth, 41(2), 160-8 | Study design, Intervention/exposure
764 | Fonseca, W.,Kirkwood, B. R.,Victora, C. G.,Fuchs, S. R.,Flores, J. A.,Misago, C. (1996). Risk factors for childhood pneumonia among the urban poor in Fortaleza, Brazil: a case--control study Bull World Health Organ, 74(2), 199-208 | Outcome
765 | Ford, K.,Labbok, M. (1993). Breast-feeding and child health in the United States J Biosoc Sci, 25(2), 187-94 | Study design
766 | Ford, R. P.,Taylor, B. J.,Mitchell, E. A.,Enright, S. A.,Stewart, A. W.,Becroft, D. M.,Scragg, R.,Hassall, I. B.,Barry, D. M.,Allen, E. M.,et al, (1993). Breastfeeding and the risk of sudden infant death syndrome Int J Epidemiol, 22(5), 885-90 | Study design
767 | Ford-Jones, E. L.,Wang, E.,Petric, M.,Corey, P.,Moineddin, R.,Fearon, M. (2000). Hospitalization for community-acquired, rotavirus-associated diarrhea: a prospective, longitudinal, population-based study during the seasonal outbreak. The Greater Toronto Area/Peel Region PRESI Study Group. Pediatric Rotavirus Epidemiology Study for Immunization Arch Pediatr Adolesc Med, 154(6), 578-85 | Study design, Participant health
768 | Forman, M. R.,Graubard, B. I.,Hoffman, H. J.,Beren, R.,Harley, E. E.,Bennett, P. (1984). The Pima Infant Feeding Study: breast feeding and gastroenteritis in the first year of life Am J Epidemiol, 119(3), 335-49 | Study design
769 | Forman, M. R.,Graubard, B. I.,Hoffman, H. J.,Beren, R.,Harley, E. E.,Bennett, P. (1984). The Pima infant feeding study: breastfeeding and respiratory infections during the first year of life Int J Epidemiol, 13(4), 447-53 | Study design, Intervention/exposure
770 | Forman, M. R.,Guptill, K. S.,Chang, D. N.,Sarov, B.,Berendes, H. W.,Naggan, L.,Hundt, G. L. (1990). Undernutrition among Bedouin Arab infants: the Bedouin Infant Feeding Study Am J Clin Nutr, 51(3), 343-9 | Outcome
771 | Forman, M. R.,Lewando-Hundt, G.,Graubard, B. I.,Chang, D.,Sarov, B.,Naggan, L.,Berendes, H. W. (1992). Factors influencing milk insufficiency and its long-term health effects: the Bedouin Infant Feeding Study Int J Epidemiol, 21(1), 53-8 | Outcome
772 | Forns, J.,Torrent, M.,Garcia-Esteban, R.,Caceres, A.,Pilar Gomila, M.,Martinez, D.,Morales, E.,Julvez, J.,Grimalt, J. O.,Sunyer, J. (2012). Longitudinal association between early life socio-environmental factors and attention function at the age 11 years Environ Res, 117(#issue#), 54-9 | Outcome
773 | Forns, J.,Vegas, O.,Julvez, J.,Garcia-Esteban, R.,Rivera, M.,Lertxundi, N.,Guxens, M.,Fano, E.,Ferrer, M.,Grellier, J.,Ibarluzea, J.,Sunyer, J. (2014). Association between child cortisol levels in saliva and neuropsychological development during the second year of life Stress Health, 30(2), 142-8 | Intervention/exposure, Outcome
774 | Foroushani, A. R.,Mohammad, K.,Mahmoodi, M.,Siassi, F. (2010). Effect of breastfeeding on cognitive performance in a British birth cohort East Mediterr Health J, 16(2), 202-8 | Outcome
775 | Forssell, G.,Hakansson, A.,Mansson, N. O. (2001). Risk factors for respiratory tract infections in children aged 2-5 years Scand J Prim Health Care, 19(2), 122-5 | Study design
776 | Forster, D. A.,Johns, H.,Amir, L. H.,McLachlan, H. L.,Moorhead, A.,Ford, R.,McEgan, K. (2013). The MILC Study—Exploring the prevalence and outcomes associated with breast milk expression: A prospective cohort study Women & Birth, 26(#issue#), S7-S7 1p | Publication status
777 | Forsyth S,Hornstra G (2001). Essential fatty acids. Maternal and infant nutrition Pract Midwife, 4(#issue#), 34-7 | Study design
778 | Forsyth, J. S.,Willatts, P.,Agostoni, C.,Bissenden, J.,Casaer, P.,Boehm, G. (2003). Long chain polyunsaturated fatty acid supplementation in infant formula and blood pressure in later childhood: follow up of a randomised controlled trial BMJ, 326(7396), 953 | Outcome
779 | Fort, P.,Lanes, R.,Dahlem, S.,Recker, B.,Weyman-Daum, M.,Pugliese, M.,Lifshitz, F. (1986). Breast feeding and insulin-dependent diabetes mellitus in children J Am Coll Nutr, 5(5), 439-41 | Outcome
780 | Fosarelli, P. D.,DeAngelis, C.,Winkelstein, J.,Mellits, E. D. (1985). Infectious illnesses in the first two years of life Pediatr Infect Dis, 4(2), 153-9 | Outcome
781 | Foulon, S.,Pingault, J. B.,Larroque, B.,Melchior, M.,Falissard, B.,Cote, S. M. (2015). Developmental predictors of inattention-hyperactivity from pregnancy to early childhood PLoS One, 10(5), e0125996 | Outcome
782 | France, G. L.,Marmer, D. J.,Steele, R. W. (1980). Breast-feeding and Salmonella infection Am J Dis Child, 134(2), 147-52 | Study design, Size of study groups
783 | Frank, A. L.,Taber, L. H.,Glezen, W. P.,Kasel, G. L.,Wells, C. R.,Paredes, A. (1982). Breast-feeding and respiratory virus infection Pediatrics, 70(2), 239-45 | Intervention/exposure
784 | Franklin, Patricia D. (2013). Exclusive Breastfeeding Duration in Relationship to Infant Risk for Overweight and Obesity at Three Years of Age #journal#, Ph.D.(#issue#), 186 p-186 p 1p | Publication status
785 | Franks, A. (1989). Breastfeeding in the neonatal unit N Z Nurs J, 82(8), 23-4 | Study design
786 | Fransoo, R. R.,Roos, N. P.,Martens, P. J.,Heaman, M.,Levin, B.,Chateau, D. (2008). How health status affects progress and performance in school: a population-based study Can J Public Health, 99(4), 344-9 | Outcome
787 | Frederiksen, B.,Kroehl, M.,Lamb, M. M.,Seifert, J.,Barriga, K.,Eisenbarth, G. S.,Rewers, M.,Norris, J. M. (2013). Infant exposures and development of type 1 diabetes mellitus: The Diabetes Autoimmunity Study in the Young (DAISY) JAMA Pediatr, 167(9), 808-15 | Outcome
788 | Fredriksson, P.,Jaakkola, N.,Jaakkola, J. J. (2007). Breastfeeding and childhood asthma: a six-year population-based cohort study BMC Pediatr, 7(#issue#), 39 | Outcome
789 | Freeman, K.,Bonuck, K. A.,Trombley, M. (2008). Breastfeeding and infant illness in low-income, minority women: a prospective cohort study of the dose-response relationship J Hum Lact, 24(1), 14-22; quiz 23-6 | Outcome
790 | Freeman, V. E.,Mulder, J.,van’t Hof, M. A.,Hoey, H. M.,Gibney, M. J. (1998). A longitudinal study of iron status in children at 12, 24 and 36 months Public Health Nutr, 1(2), 93-100 | Intervention/exposure
791 | Friel, J. K.,Andrews, W. L.,Simmons, B. S.,L’Abbe, M. R.,Mercer, C.,MacDonald, A.,McCloy, U. R. (1997). Evaluation of full-term infants fed an evaporated milk formula Acta Paediatr, 86(5), 448-53 | Size of study groups
792 | Froom, J.,Culpepper, L.,Green, L. A.,de Melker, R. A.,Grob, P.,Heeren, T.,van Balen, F. (2001). A cross-national study of acute otitis media: risk factors, severity, and treatment at initial visit. Report from the International Primary Care Network (IPCN) and the Ambulatory Sentinel Practice Network (ASPN) J Am Board Fam Pract, 14(6), 406-17 | Study design
793 | Froozani, M. D.,Malekafzali, H.,Bahrini, B. (1980). Growth of a group of low income infants in the first year of life J Trop Pediatr, 26(3), 96-8 | Study design, Intervention/exposure
794 | Froozani, M. D.,Permehzadeh, K.,Motlagh, A. R.,Golestan, B. (1999). Effect of breastfeeding education on the feeding pattern and health of infants in their first 4 months in the Islamic Republic of Iran Bull World Health Organ, 77(5), 381-5 | Outcome
795 | Fruhwirth, M.,Heininger, U.,Ehlken, B.,Petersen, G.,Laubereau, B.,Moll-Schuler, I.,Mutz, I.,Forster, J. (2001). International variation in disease burden of rotavirus gastroenteritis in children with community- and nosocomially acquired infection Pediatr Infect Dis J, 20(8), 784-91 | Participant health
796 | Frye, C.,Heinrich, J. (2003). Trends and predictors of overweight and obesity in East German children Int J Obes Relat Metab Disord, 27(8), 963-9 | Study design
797 | Fuchs, S. C.,Victora, C. G. (2002). Risk and prognostic factors for diarrheal disease in Brazilian infants: a special case-control design application Cad Saude Publica, 18(3), 773-82 | Outcome
798 | Fuchs, S. C.,Victora, C. G.,Martines, J. (1996). Case-control study of risk of dehydrating diarrhoea in infants in vulnerable period after full weaning BMJ, 313(7054), 391-4 | Outcome
799 | Fuiano, N.,Rapa, A.,Monzani, A.,Pietrobelli, A.,Diddi, G.,Limosani, A.,Bona, G. (2008). Prevalence and risk factors for overweight and obesity in a population of Italian schoolchildren: a longitudinal study J Endocrinol Invest, 31(11), 979-84 | Intervention/exposure
800 | Fujita, H.,Okada, T.,Inami, I.,Makimoto, M.,Hosono, S.,Minato, M.,Takahashi, S.,Mugishima, H.,Yamamoto, T. (2008). Low-density lipoprotein profile changes during the neonatal period J Perinatol, 28(5), 335-40 | Size of study groups, Intervention/exposure
801 | Fujiwara, T.,Oguni, T.,Unishi, G.,Tanabe, T.,Ohbayashi, K.,Kaneko, K. (2014). Factors related to patterns of body mass index in early infancy: 18 month longitudinal study Pediatr Int, 56(3), 406-10 | Intervention/exposure
802 | Fullerton, K. E.,Ingram, L. A.,Jones, T. F.,Anderson, B. J.,McCarthy, P. V.,Hurd, S.,Shiferaw, B.,Vugia, D.,Haubert, N.,Hayes, T.,Wedel, S.,Scallan, E.,Henao, O.,Angulo, F. J. (2007). Sporadic campylobacter infection in infants: a population-based surveillance case-control study Pediatr Infect Dis J, 26(1), 19-24 | Outcome
803 | Gabriel, C. G.,Corso, A. C.,Caldeira, G. V.,Gimeno, S. G.,Schmitz Bde, A.,de Vasconcelos Fde, A. (2010). Overweight and obesity related factors in schoolchildren in Santa Catarina State, Brazil Arch Latinoam Nutr, 60(4), 332-9 | Study design
804 | Gabriele, C.,Silva, L. M.,Arends, L. R.,Raat, H.,Moll, H. A.,Hofman, A.,Jaddoe, V. W.,de Jongste, J. C. (2012). Early respiratory morbidity in a multicultural birth cohort: the Generation R Study Eur J Epidemiol, 27(6), 453-62 | Outcome
805 | Gaffney, K. F.,Kitsantas, P.,Cheema, J. (2012). Clinical practice guidelines for feeding behaviors and weight-for-age at 12 months: a secondary analysis of the Infant Feeding Practices Study II Worldviews Evid Based Nurs, 9(4), 234-42 | Intervention/exposure
806 | Galan-Gonzalez AF,Aznar-Martin T,Cabrera-Dominguez ME,Dominguez-Reyes A (2014). Do breastfeeding and bottle feeding influence occlusal parameters? Breastfeed Med, 9(#issue#), 24-8 | Study design
807 | Galán-Gónzalez, A. F.,Aznar-Martín, T.,Cabrera-Domínguez, M. E.,Domínguez-Reyes, A. (2014). Do breastfeeding and bottle feeding influence occlusal parameters? Breastfeeding Medicine, 9(1), 24-28 | Study design
808 | Gale, C. R.,Marriott, L. D.,Martyn, C. N.,Limond, J.,Inskip, H. M.,Godfrey, K. M.,Law, C. M.,Cooper, C.,West, C.,Robinson, S. M. (2010). Breastfeeding, the use of docosahexaenoic acid-fortified formulas in infancy and neuropsychological function in childhood Arch Dis Child, 95(3), 174-9 | Outcome
809 | Gale, C. R.,Martyn, C. N. (1996). Breastfeeding, dummy use, and adult intelligence Lancet, 347(9008), 1072-5 | Outcome
810 | Gale, C. R.,Martyn, C. N.,Marriott, L. D.,Limond, J.,Crozier, S.,Inskip, H. M.,Godfrey, K. M.,Law, C. M.,Cooper, C.,Robinson, S. M. (2009). Dietary patterns in infancy and cognitive and neuropsychological function in childhood Journal of Child Psychology and Psychiatry and Allied Disciplines, 50(7), 816-823 | Intervention/exposure
811 | Gale, C.,Thomas, E. L.,Jeffries, S.,Durighel, G.,Logan, K. M.,Parkinson, J. R.,Uthaya, S.,Santhakumaran, S.,Bell, J. D.,Modi, N. (2014). Adiposity and hepatic lipid in healthy full-term, breastfed, and formula-fed human infants: a prospective short-term longitudinal cohort study Am J Clin Nutr, 99(5), 1034-40 | Size of study groups
812 | Galler, J. R.,Harrison, R. H.,Ramsey, F.,Forde, V.,Butler, S. C. (2000). Maternal depressive symptoms affect infant cognitive development in Barbados J Child Psychol Psychiatry, 41(6), 747-57 | Intervention/exposure
813 | Galler, J. R.,Ramsey, F. C.,Harrison, R. H.,Brooks, R.,Weiskopf-Bock, S. (1998). Infant feeding practices in Barbados predict later growth J Nutr, 128(8), 1328-35 | Intervention/exposure
814 | Galler, J. R.,Ramsey, F. C.,Harrison, R. H.,Taylor, J.,Cumberbatch, G.,Forde, V. (2004). Postpartum maternal moods and infant size predict performance on a national high school entrance examination J Child Psychol Psychiatry, 45(6), 1064-75 | Outcome
815 | Galli, E.,Picardo, M.,Chini, L.,Passi, S.,Moschese, V.,Terminali, O.,Paone, F.,Fraioli, G.,Rossi, P. (1994). Analysis of polyunsaturated fatty acids in newborn sera: a screening tool for atopic disease? Br J Dermatol, 130(6), 752-6 | Size of study groups
816 | Gallico R,Hokemeyer C (1987). SIDS project offers delactation advice NAACOG Newsl, 14(#issue#), 4-5 | Study design
817 | Garcia, M. V.,Azevedo, M. F.,Testa, J. R.,Luiz, C. B. (2012). The influence of the type of breastfeeding on middle ear conditions in infants Braz J Otorhinolaryngol, 78(1), 8-14 | Study design, Size of study groups
818 | Garcia-Marcos, L.,Mallol, J.,Sole, D.,Brand, P. L. (2010). International study of wheezing in infants: risk factors in affluent and non-affluent countries during the first year of life Pediatr Allergy Immunol, 21(5), 878-88 | Study design
819 | Garcia-Marcos, L.,Mallol, J.,Sole, D.,Brand, P. L.,Sanchez-Bahillo, M.,Sanchez-Solis, M. (2013). Latitude modifies the effect size of factors related to recurrent wheeze in the first year of life Respir Med, 107(5), 665-72 | Study design, Outcome
820 | Garden, F. L.,Marks, G. B.,Simpson, J. M.,Webb, K. L. (2012). Body mass index (BMI) trajectories from birth to 11.5 years: relation to early life food intake Nutrients, 4(10), 1382-98 | Outcome
821 | Garmendia, M. L.,Corvalan, C.,Araya, M.,Casanello, P.,Kusanovic, J. P.,Uauy, R. (2015). Effectiveness of a normative nutrition intervention (diet, physical activity and breastfeeding) on maternal nutrition and offspring growth: the Chilean maternal and infant nutrition cohort study (CHiMINCs) BMC Pregnancy Childbirth, 15(#issue#), 175 | Study design, Intervention/exposure
822 | Garry, P. J.,Owen, G. M.,Hooper, E. M.,Gilbert, B. A. (1981). Iron absorption from human milk and formula with and without iron supplementation Pediatr Res, 15(5), 822-8 | Intervention/exposure
823 | Garza, C. (2014). The INTERGROWTH-21st project and the multicenter growth reference study: enhanced opportunities for monitoring growth from early pregnancy to 5 years of age Breastfeed Med, 9(7), 341-4 | Study design
824 | Garza, C.,Borghi, E.,Onyango, A. W.,de Onis, M. (2013). Parental height and child growth from birth to 2 years in the WHO Multicentre Growth Reference Study Matern Child Nutr, 9 Suppl 2(#issue#), 58-68 | Outcome
825 | Gathwala, G.,Narang, A. (1995). Breast is best Indian J Pediatr, 62(6), 687-90 | Study design
826 | Gearry, R. B.,Richardson, A. K.,Frampton, C. M.,Dodgshun, A. J.,Barclay, M. L. (2010). Population-based cases control study of inflammatory bowel disease risk factors J Gastroenterol Hepatol, 25(2), 325-33 | Outcome
827 | Geller-Bernstein, G.,Kenett, R.,Weisglass, L.,Tsur, S.,Lahav, M.,Levin, S. (1987). Atopic babies with wheezy bronchitis. Follow-up study relating prognosis to sequential IgE values, type of early infant feeding, exposure to parental smoking and incidence of lower respiratory tract infections Allergy, 42(2), 85-91 | Outcome
828 | Gerrard, J. W. (1984). Allergies in breastfed babies to foods ingested by the mother (review) Clin Rev Allergy, 2(2), 143-9 | Study design
829 | Gerrard, J. W.,Shenassa, M. (1983). Food allergy: two common types as seen in breast and formula fed babies Ann Allergy, 50(6), 375-9 | Study design
830 | Gessner, B. D.,Plotnik, J.,Muth, P. T. (2003). 25-hydroxyvitamin D levels among healthy children in Alaska J Pediatr, 143(4), 434-7 | Study design, Intervention/exposure
831 | Gessner, B. D.,Ussery, X. T.,Parkinson, A. J.,Breiman, R. F. (1995). Risk factors for invasive disease caused by Streptococcus pneumoniae among Alaska native children younger than two years of age Pediatr Infect Dis J, 14(2), 123-8 | Study design, Size of study groups
832 | Ghosh, S.,Sengupta, P. G.,Mondal, S. K.,Banu, M. K.,Gupta, D. N.,Sircar, B. K. (1997). Risk behavioural practices of rural mothers as determinants of childhood diarrhoea J Commun Dis, 29(1), 7-14 | Country
833 | Ghys, A.,Bakker, E.,Hornstra, G.,van den Hout, M. (2002). Red blood cell and plasma phospholipid arachidonic and docosahexaenoic acid levels at birth and cognitive development at 4 years of age Early Hum Dev, 69(1-2), 83-90 | Study design
834 | Gianino, P.,Mastretta, E.,Longo, P.,Laccisaglia, A.,Sartore, M.,Russo, R.,Mazzaccara, A. (2002). Incidence of nosocomial rotavirus infections, symptomatic and asymptomatic, in breast-fed and non-breast-fed infants Journal of Hospital Infection, 50(1), 13-17 | Study design
835 | Gianni, M. L.,Roggero, P.,Baudry, C.,Ligneul, A.,Morniroli, D.,Garbarino, F.,le Ruyet, P.,Mosca, F. (2012). The influence of a formula supplemented with dairy lipids and plant oils on the erythrocyte membrane omega-3 fatty acid profile in healthy full-term infants: a double-blind randomized controlled trial BMC Pediatr, 12(#issue#), 164 | Intervention/exposure, Size of study groups
836 | Gianni, M. L.,Roggero, P.,Morlacchi, L.,Garavaglia, E.,Piemontese, P.,Mosca, F. (2014). Formula-fed infants have significantly higher fat-free mass content in their bodies than breastfed babies Acta Paediatr, 103(7), e277-81 | Intervention/exposure
837 | Gibbs, B. G.,Forste, R. (2014). Breastfeeding, parenting, and early cognitive development J Pediatr, 164(3), 487-93 | Outcome
838 | Gibbs, B. G.,Forste, R. (2014). Socioeconomic status, infant feeding practices and early childhood obesity Pediatr Obes, 9(2), 135-46 | Intervention/exposure
839 | Gibson RA,Makrides M,Clark KJ,Neumann MA,Lines DR (1992). Long chain omega 3 polyunsaturates in formula-fed term infants Adv Exp Med Biol, 318(#issue#), 341-5 | Size of study groups
840 | Gibson, R. A.,Neumann, M. A.,Makrides, M. (1997). Effect of increasing breast milk docosahexaenoic acid on plasma and erythrocyte phospholipid fatty acids and neural indices of exclusively breast fed infants Eur J Clin Nutr, 51(9), 578-84 | Outcome
841 | Gibson-Davis, C. M.,Brooks-Gunn, J. (2006). Breastfeeding and verbal ability of 3-year-olds in a multicity sample Pediatrics, 118(5), e1444-51 | Outcome
842 | Gigante, D. P.,Horta, B. L.,Lima, R. C.,Barros, F. C.,Victora, C. G. (2006). Early life factors are determinants of female height at age 19 years in a population-based birth cohort (Pelotas, Brazil) J Nutr, 136(2), 473-8 | Outcome
843 | Gil, A.,Lozano, E.,De-Lucchi, C.,Maldonado, J.,Molina, J. A.,Pita, M. (1988). Changes in the fatty acid profiles of plasma lipid fractions induced by dietary nucleotides in infants born at term Eur J Clin Nutr, 42(6), 473-81 | Size of study groups
844 | Gilat, T.,Hacohen, D.,Lilos, P.,Langman, M. J. (1987). Childhood factors in ulcerative colitis and Crohn’s disease. An international cooperative study Scand J Gastroenterol, 22(8), 1009-24 | Outcome
845 | Gilbert, R. (1994). The changing epidemiology of SIDS Arch Dis Child, 70(5), 445-9 | Study design
846 | Gilbert, R. E.,Wigfield, R. E.,Fleming, P. J.,Berry, P. J.,Rudd, P. T. (1995). Bottle feeding and the sudden infant death syndrome BMJ, 310(6972), 88-90 | Outcome
847 | Gillman, M. W.,Rifas-Shiman, S. L.,Berkey, C. S.,Frazier, A. L.,Rockett, H. R.,Camargo, C. A., Jr.,Field, A. E.,Colditz, G. A. (2006). Breast-feeding and overweight in adolescence: within-family analysis [corrected] Epidemiology, 17(1), 112-4 | Outcome
848 | Gillman, M. W.,Rifas-Shiman, S. L.,Camargo, C. A., Jr.,Berkey, C. S.,Frazier, A. L.,Rockett, H. R.,Field, A. E.,Colditz, G. A. (2001). Risk of overweight among adolescents who were breastfed as infants JAMA, 285(19), 2461-7 | Study design
849 | Gillman, M. W.,Rifas-Shiman, S. L.,Kleinman, K.,Oken, E.,Rich-Edwards, J. W.,Taveras, E. M. (2008). Developmental origins of childhood overweight: potential public health impact Obesity (Silver Spring), 16(7), 1651-6 | Outcome
850 | Gimenez-Sanchez, F.,Delgado-Rubio, A.,Martinon-Torres, F.,Bernaola-Iturbe, E. (2010). Multicenter prospective study analysing the role of rotavirus on acute gastroenteritis in Spain Acta Paediatr, 99(5), 738-42 | Study design, Participant health
851 | Gimeno, S. G.,de Souza, J. M. (1997). IDDM and milk consumption. A case-control study in Sao Paulo, Brazil Diabetes Care, 20(8), 1256-60 | Outcome
852 | Giovannini, M.,Agostoni, C.,Fiocchi, A.,Bellu, R.,Trojan, S.,Riva, E. (1994). Antigen-reduced infant formulas versus human milk: growth and metabolic parameters in the first 6 months of life J Am Coll Nutr, 13(4), 357-63 | Size of study groups
853 | Giovannini, M.,Verduci, E.,Zuccotti, G.,Biasucci, G.,Podesta, A.,Rottoli, A.,Gregori, D.,Ballali, S.,Banderali, G.,Riva, E.,Ghisleni, D.,Pogliani, L.,Cicero, C.,Tonella, M.,Frugnoli, I. (2013). Safety of a formula supplemented with galacto-oligosaccharides in term infants International journal of probiotics & prebiotics, 8(2-3), 67-74 | Intervention/exposure
854 | Giovannini, M.,Verduci, E.,Zuccotti, G.,Biasucci, G.,Podesta, A.,Rottoli, A.,Gregori, D.,Ballali, S.,Soldi, S.,Banderali, G.,Ghisleni, D.,Riva, E. (2013). Prebiotic effect of a formula supplemented with galacto-oligosaccharides in term infants: A randomized multicenter trial Annals of nutrition & metabolism, 63(#issue#), 1667 | Study design
855 | Gishti, O.,Gaillard, R.,Durmus, B.,Hofman, A.,Duijts, L.,Franco, O. H.,Jaddoe, V. W. (2014). Infant diet and metabolic outcomes in school-age children. The Generation R Study Eur J Clin Nutr, 68(9), 1008-15 | Outcome
856 | Gishti, O.,Jaddoe, V. W.,Duijts, L.,Franco, O. H.,Hofman, A.,Ikram, M. K.,Gaillard, R. (2015). Influence of breastfeeding on retinal vessel calibers in school-age children. The Generation R Study Eur J Clin Nutr, #volume#(#issue#), #Pages# | Outcome
857 | Giugliano, L. G.,Meyer, C. J.,Arantes, L. C.,Ribeiro, S. T.,Giugliano, R. (1993). Mannose-resistant haemagglutination (MRHA) and haemolysin (Hly) production of strains of Escherichia coli isolated from children with diarrhoea: effect of breastfeeding J Trop Pediatr, 39(3), 183-7 | Study design, Participant health
858 | Giwercman, C.,Halkjaer, L. B.,Jensen, S. M.,Bonnelykke, K.,Lauritzen, L.,Bisgaard, H. (2010). Increased risk of eczema but reduced risk of early wheezy disorder from exclusive breast-feeding in high-risk infants J Allergy Clin Immunol, 125(4), 866-71 | Intervention/exposure
859 | Glatthaar, C.,Whittall, D. E.,Welborn, T. A.,Gibson, M. J.,Brooks, B. H.,Ryan, M. M.,Byrne, G. C. (1988). Diabetes in Western Australian children: descriptive epidemiology Med J Aust, 148(3), 117-23 | Intervention/exposure
860 | Gliddon, M. L.,Sutton, G. (2001). Prediction of 8-month MEE from neonatal risk factors and test results in SCBU and full-term babies British Journal of Audiology, 35(1), 77-85 | Non-human sample, Participant health
861 | Glueck, C. J.,Salehi, M.,Sieve, L.,Wang, P. (2006). Growth, motor, and social development in breast- and formula-fed infants of metformin-treated women with polycystic ovary syndrome J Pediatr, 148(5), 628-632 | Outcome
862 | Gokcay, G.,Turan, J. M.,Partalci, A.,Neyzi, O. (2003). Growth of infants during the first year of life according to feeding regimen in the first 4 months J Trop Pediatr, 49(1), 6-12 | Intervention/exposure
863 | Goldfield, G. S.,Paluch, R.,Keniray, K.,Hadjiyannakis, S.,Lumb, A. B.,Adamo, K. (2006). Effects of breastfeeding on weight changes in family-based pediatric obesity treatment J Dev Behav Pediatr, 27(2), 93-7 | Participant health
864 | Golding, J.,Rogers, I. S.,Emmett, P. M. (1997). Breast feeding: benefits and hazards. Methodology and summary of results Early Hum Dev, 49 Suppl(#issue#), S1-6 | Study design
865 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Avila, O. (2003). Influence of breast-feeding on mental and psychomotor development Clin Pediatr (Phila), 42(1), 35-42 | Outcome
866 | Gomez-Sanchiz, M.,Canete, R.,Rodero, I.,Baeza, J. E.,Gonzalez, J. A. (2004). Influence of breast-feeding and parental intelligence on cognitive development in the 24-month-old child Clin Pediatr (Phila), 43(8), 753-61 | Outcome
867 | Gong, Y. H.,Ji, C. Y.,Zheng, X. X.,Shan, J. P.,Hou, R. (2008). Correlation of 4-month infant feeding modes with their growth and iron status in Beijing Chin Med J (Engl), 121(5), 392-8 | Intervention/exposure
868 | Gonzalez-Casanova, I.,Stein, A.,Hao, W.,Feregrino, R.,Romieu, I.,Barraza-Villarreal, A.,Rivera, J.,Martorell, R.,Ramakrishnan, U. (2014). Height and BMI at five years of age following prenatal supplementation with docosahexaenoic acid in Mexico FASEB journal, 28(1 suppl. 1), #Pages# | Publication status
869 | Gónzalez-Iglesias, H.,De La Flor St Remy, R. R.,López-Sastre, J.,Fernández-Colomer, B.,Ibáñez-Fernández, A.,Solís, G.,Sanz-Medel, A.,Fernández-Sánchez, M. L. (2012). Efficiency of iodine supplementation, as potassium iodide, during lactation: A study in neonates and their mothers Food Chemistry, 133(3), 859-865 | Intervention/exposure
870 | Gopalan, S.,Puri, R. K. (1992). Breast feeding and infant growth Indian Pediatr, 29(8), 1079-86 | Study design
871 | Gopinath, V. K.,Muda, W. A. (2005). Assessment of growth and feeding practices in children with cleft lip and palate Southeast Asian J Trop Med Public Health, 36(1), 254-8 | Intervention/exposure, Outcome
872 | Gordon, M. (1995). Why breastfeeding is best for babies Health Visit, 68(5), 203-4 | Study design
873 | Gordon, R. R.,Noble, D. A.,Ward, A. M.,Allen, R. (1982). Immunoglobulin E and the eczema-asthma syndrome in early childhood Lancet, 1(8263), 72-4 | Outcome
874 | Gore, C.,Custovic, A.,Tannock, G. W.,Munro, K.,Kerry, G.,Johnson, K.,Peterson, C.,Morris, J.,Chaloner, C.,Murray, C. S.,Woodcock, A. (2012). Treatment and secondary prevention effects of the probiotics Lactobacillus paracasei or Bifidobacterium lactis on early infant eczema: randomized controlled trial with follow-up until age 3 years Clin Exp Allergy, 42(1), 112-22 | Participant health, Size of study groups
875 | Gore, C.,Munro, K.,Lay, C.,Bibiloni, R.,Morris, J.,Woodcock, A.,Custovic, A.,Tannock, G. W. (2008). Bifidobacterium pseudocatenulatum is associated with atopic eczema: a nested case-control study investigating the fecal microbiota of infants J Allergy Clin Immunol, 121(1), 135-40 | Size of study groups
876 | Gore, N.,Emerson, E.,Brady, S. (2015). Rates of breastfeeding and exposure to socio-economic adversity amongst children with intellectual disability Res Dev Disabil, 39(#issue#), 12-9 | Outcome
877 | Gormally, S. M.,Matthews, T. G. (1992). Contemporary risk factors for sudden infant death in an Irish population--a case control study Ir J Med Sci, 161(5), 131-4 | Outcome
878 | Grabenhenrich, L. B.,Gough, H.,Reich, A.,Eckers, N.,Zepp, F.,Nitsche, O.,Forster, J.,Schuster, A.,Schramm, D.,Bauer, C. P.,Hoffmann, U.,Beschorner, J.,Wagner, P.,Bergmann, R.,Bergmann, K.,Matricardi, P. M.,Wahn, U.,Lau, S.,Keil, T. (2014). Early-life determinants of asthma from birth to age 20 years: a German birth cohort study J Allergy Clin Immunol, 133(4), 979-88 | Outcome
879 | Gracey, M. (1989). Maternal health, breast-feeding and infant nutrition in Australian aborigines Acta Paediatr Jpn, 31(4), 377-80 | Study design
880 | Grainger, M. (2006). Breastfeeding can reduce infant infections and health care costs Ala Nurse, 33(3), 23 | Study design
881 | Grandjean, P.,Poulsen, L. K.,Heilmann, C.,Steuerwald, U.,Weihe, P. (2010). Allergy and sensitization during childhood associated with prenatal and lactational exposure to marine pollutants Environ Health Perspect, 118(10), 1429-33 | Outcome
882 | Granot, E.,Golan, D.,Berry, E. M. (2000). Breast-fed and formula-fed infants do not differ in immunocompetent cell cytokine production despite differences in cell membrane fatty acid composition Am J Clin Nutr, 72(5), 1202-5 | Size of study groups
883 | Graves, J.,Grandhe, S.,Weinfurtner, K.,Krupp, L.,Belman, A.,Chitnis, T.,Ness, J.,Weinstock-Guttman, B.,Gorman, M.,Patterson, M.,Rodriguez, M.,Lotze, T.,Aaen, G.,Mowry, E. M.,Rose, J. W.,Simmons, T.,Casper, T. C.,James, J.,Waubant, E. (2014). Protective environmental factors for neuromyelitis optica Neurology, 83(21), 1923-9 | Outcome
884 | Greasley, V. (1986). Breast feeding Nursing (Lond), 3(2), 63-70 | Study design
885 | Greco, L.,Auricchio, S.,Mayer, M.,Grimaldi, M. (1988). Case control study on nutritional risk factors in celiac disease J Pediatr Gastroenterol Nutr, 7(3), 395-9 | Outcome
886 | Green, Ken (2012). UC Denver Study: Breastfeeding Can Prevent Diabetes-Related Childhood Obesity Inside Childbirth Education, #volume#(#issue#), 10-10 1p | Study design
887 | Greene, L. C.,Lucas, A.,Livingstone, M. B.,Harland, P. S.,Baker, B. A. (1995). Relationship between early diet and subsequent cognitive performance during adolescence Biochem Soc Trans, 23(2), 376S | Outcome
888 | Greenop, K. R.,Bailey, H. D.,Miller, M.,Scott, R. J.,Attia, J.,Ashton, L. J.,Downie, P.,Armstrong, B. K.,Milne, E. (2015). Breastfeeding and nutrition to 2 years of age and risk of childhood acute lymphoblastic leukemia and brain tumors Nutr Cancer, 67(3), 431-41 | Outcome
889 | Greer FR,Tsang RC (1983). Vitamin D in human milk: is there enough? J Pediatr Gastroenterol Nutr, 2 Suppl 1(#issue#), S277-81 | Study design
890 | Greer MH,Tendan SL (1998). Early childhood dental caries in Hawai’i Hawaii Dent J, 29(#issue#), 10, 14 | Study design
891 | Greer, F. R.,Marshall, S. (1989). Bone mineral content, serum vitamin D metabolite concentrations, and ultraviolet B light exposure in infants fed human milk with and without vitamin D2 supplements J Pediatr, 114(2), 204-12 | Size of study groups
892 | Greer, F. R.,Searcy, J. E.,Levin, R. S.,Steichen, J. J.,Steichen-Asche, P. S.,Tsang, R. C. (1982). Bone mineral content and serum 25-hydroxyvitamin D concentrations in breast-fed infants with and without supplemental vitamin D: one-year follow-up J Pediatr, 100(6), 919-22 | Size of study groups
893 | Greibe, E.,Lildballe, D. L.,Streym, S.,Vestergaard, P.,Rejnmark, L.,Mosekilde, L.,Nexo, E. (2013). Cobalamin and haptocorrin in human milk and cobalamin-related variables in mother and child: a 9-mo longitudinal study Am J Clin Nutr, 98(2), 389-95 | Intervention/exposure
894 | Grguric, J.,Wen, R. A.,Kylberg, E.,Ashmore, S.,Macenroe, T. (2012). International perspectives on the Baby-Friendly Initiative J Hum Lact, 28(3), 281-4 | Study design
895 | Grice, A. C.,McGlashan, N. D. (1981). Obstetric factors in 171 sudden infant deaths in Tasmania, 1970--1976 Med J Aust, 1(1), 26-31 | Outcome
896 | Griffiths, L. J.,Hawkins, S. S.,Cole, T. J.,Dezateux, C. (2010). Risk factors for rapid weight gain in preschool children: Findings from a UK-wide prospective study International Journal of Obesity, 34(4), 624-632 | Outcome
897 | Griffiths, L. J.,Smeeth, L.,Hawkins, S. S.,Cole, T. J.,Dezateux, C. (2009). Effects of infant feeding practice on weight gain from birth to 3 years Arch Dis Child, 94(8), 577-82 | Outcome
898 | Grimshaw, K. E.,Maskell, J.,Oliver, E. M.,Morris, R. C.,Foote, K. D.,Mills, E. N.,Roberts, G.,Margetts, B. M. (2013). Introduction of complementary foods and the relationship to food allergy Pediatrics, 132(6), e1529-38 | Outcome
899 | Grjibovski, A. M.,Bygren, L. O.,Yngve, A.,Sjostrom, M. (2004). Social variations in infant growth performance in Severodvinsk, Northwest Russia: community-based cohort study Croat Med J, 45(6), 757-63 | Outcome
900 | Groen-Blokhuis, M. M.,Franic, S.,van Beijsterveldt, C. E.,de Geus, E.,Bartels, M.,Davies, G. E.,Ehli, E. A.,Xiao, X.,Scheet, P. A.,Althoff, R.,Hudziak, J. J.,Middeldorp, C. M.,Boomsma, D. I. (2013). A prospective study of the effects of breastfeeding and FADS2 polymorphisms on cognition and hyperactivity/attention problems Am J Med Genet B Neuropsychiatr Genet, 162B(5), 457-65 | Outcome
901 | Groenwold, R. H.,Tilling, K.,Moons, K. G.,Hoes, A. W.,van der Ent, C. K.,Kramer, M. S.,Martin, R. M.,Sterne, J. A. (2014). Breast-feeding and health consequences in early childhood: is there an impact of time-dependent confounding? Ann Nutr Metab, 65(2-3), 139-48 | Intervention/exposure
902 | Grossman, X.,Chaudhuri, J. H.,Feldman-Winter, L.,Merewood, A. (2012). Neonatal weight loss at a US Baby-Friendly Hospital J Acad Nutr Diet, 112(3), 410-3 | Size of study groups
903 | Grube, M. M.,von der Lippe, E.,Schlaud, M.,Brettschneider, A. K. (2015). Does breastfeeding help to reduce the risk of childhood overweight and obesity? A propensity score analysis of data from the KiGGS study PLoS One, 10(3), e0122534 | Study design
904 | Gruber, C.,van Stuijvenberg, M.,Mosca, F.,Moro, G.,Chirico, G.,Braegger, C. P.,Riedler, J.,Boehm, G.,Wahn, U. (2010). Reduced occurrence of early atopic dermatitis because of immunoactive prebiotics among low-atopy-risk infants J Allergy Clin Immunol, 126(4), 791-7 | Intervention/exposure
905 | Gruber, M.,Marshall, J. R.,Zielezny, M.,Lance, P. (1996). A case-control study to examine the influence of maternal perinatal behaviors on the incidence of Crohn’s disease Gastroenterol Nurs, 19(2), 53-9 | Study design
906 | Grummer-Strawn, L. M.,Li, R.,Perrine, C. G.,Scanlon, K. S.,Fein, S. B. (2014). Infant feeding and long-term outcomes: results from the year 6 follow-up of children in the Infant Feeding Practices Study II Pediatrics, 134 Suppl 1(#issue#), S1-3 | Study design
907 | Grummer-Strawn, L. M.,Mei, Z. (2004). Does breastfeeding protect against pediatric overweight? Analysis of longitudinal data from the Centers for Disease Control and Prevention Pediatric Nutrition Surveillance System Pediatrics, 113(2), e81-6 | Outcome
908 | Gruskay, F. L. (1982). Comparison of breast, cow, and soy feedings in the prevention of onset of allergic disease: a 15-year prospective study Clin Pediatr (Phila), 21(8), 486-91 | Intervention/exposure
909 | Gruszfeld, D.,Weber, M.,Nowakowska-Rysz, M.,Janas, R.,Kozlik-Feldmann, R.,Xhonneux, A.,Carlier, C.,Riva, E.,Verduci, E.,Closa-Monasterolo, R.,Escribano, J.,Dobrzanska, A.,Koletzko, B. (2015). Protein intake in infancy and carotid intima media thickness at 5 years--a secondary analysis from a randomized trial Ann Nutr Metab, 66(1), 51-9 | Intervention/exposure
910 | Gubbels, J. S.,Thijs, C.,Stafleu, A.,van Buuren, S.,Kremers, S. P. (2011). Association of breast-feeding and feeding on demand with child weight status up to 4 years Int J Pediatr Obes, 6(2-2), e515-22 | Outcome
911 | Gudino, S.,Rojas, N.,Castro, C.,Rodriguez, M.,Vega, M.,Lopez, L. M. (2007). Colonization of mutans streptococci in Costa Rican children from a high-risk population J Dent Child (Chic), 74(1), 36-40 | Study design
912 | Guedes, H. T.,Souza, L. S. (2009). Exposure to maternal smoking in the first year of life interferes in breast-feeding protective effect against the onset of respiratory allergy from birth to 5 yr Pediatr Allergy Immunol, 20(1), 30-4 | Intervention/exposure
913 | Guerrero, M. L.,Moreno-Espinosa, S.,Tuz-Dzib, F.,Solis-Albino, J.,Ortega-Gallegos, H.,Ruiz-Palacios, G. M. (2004). Breastfeeding and natural colonization with Lactobacillus spp as protection against rotavirus-associated diarrhea Adv Exp Med Biol, 554(#issue#), 451-5 | Publication status
914 | Guesnet, P.,Pugo-Gunsam, P.,Maurage, C.,Pinault, M.,Giraudeau, B.,Alessandri, J. M.,Durand, G.,Antoine, J. M.,Couet, C. (1999). Blood lipid concentrations of docosahexaenoic and arachidonic acids at birth determine their relative postnatal changes in term infants fed breast milk or formula Am J Clin Nutr, 70(2), 292-8 | Size of study groups
915 | Guibas, G. V.,Xepapadaki, P.,Moschonis, G.,Douladiris, N.,Filippou, A.,Tsirigoti, L.,Manios, Y.,Papadopoulos, N. G. (2013). Breastfeeding and wheeze prevalence in pre-schoolers and pre-adolescents: the Genesis and Healthy Growth studies Pediatr Allergy Immunol, 24(8), 772-81 | Study design
916 | Guldan, G. S.,Fan, H. C.,Ma, X.,Ni, Z. Z.,Xiang, X.,Tang, M. Z. (2000). Culturally appropriate nutrition education improves infant feeding and growth in rural Sichuan, China J Nutr, 130(5), 1204-11 | Study design, Outcome
917 | Gulick EE (1986). The effects of breast-feeding on toddler health Pediatr Nurs, 12(#issue#), 51-4 | Outcome
918 | Gulick, E. E. (1983). Infant health and breast-feeding Pediatr Nurs, 9(5), 359-62, 389 | Study design
919 | Gunderson, E. P. (2007). Breastfeeding after gestational diabetes pregnancy: subsequent obesity and type 2 diabetes in women and their offspring Diabetes Care, 30 Suppl 2(#issue#), S161-8 | Study design
920 | Gunderson, E. P.,Hurston, S. R.,Dewey, K. G.,Faith, M. S.,Charvat-Aguilar, N.,Khoury, V. C.,Nguyen, V. T.,Quesenberry, C. P., Jr. (2015). The study of women, infant feeding and type 2 diabetes after GDM pregnancy and growth of their offspring (SWIFT Offspring study): prospective design, methodology and baseline characteristics BMC Pregnancy Childbirth, 15(#issue#), 150 | Study design
921 | Gungor, D. E.,Paul, I. M.,Birch, L. L.,Bartok, C. J. (2010). Risky vs rapid growth in infancy: refining pediatric screening for childhood overweight Arch Pediatr Adolesc Med, 164(12), 1091-7 | Outcome
922 | Gunnarsdottir, I.,Aspelund, T.,Birgisdottir, B. E.,Benediktsson, R.,Gudnason, V.,Thorsdottir, I. (2007). Infant feeding patterns and midlife erythrocyte sedimentation rate Acta Paediatr, 96(6), 852-6 | Intervention/exposure
923 | Gunnarsdottir, I.,Schack-Nielsen, L.,Michaelsen, K. F.,Sorensen, T. I.,Thorsdottir, I. (2010). Infant weight gain, duration of exclusive breast-feeding and childhood BMI - two similar follow-up cohorts Public Health Nutr, 13(2), 201-7 | Outcome
924 | Gunther, A. L.,Walz, H.,Kroke, A.,Wudy, S. A.,Riedel, C.,von Kries, R.,Joslowski, G.,Remer, T.,Cheng, G.,Buyken, A. E. (2013). Breastfeeding and its prospective association with components of the GH-IGF-Axis, insulin resistance and body adiposity measures in young adulthood--insights from linear and quantile regression analysis PLoS One, 8(11), e79436 | Intervention/exposure
925 | Guo, A. Y.,Stevens, B. W.,Wilson, R. G.,Russell, C. N.,Cohen, M. A.,Sturgeon, H. C.,Thornton, A.,Giallourakis, C.,Khalili, H.,Nguyen, D. D.,Sauk, J.,Yajnik, V.,Xavier, R. J.,Ananthakrishnan, A. N. (2014). Early life environment and natural history of inflammatory bowel diseases BMC Gastroenterol, 14(#issue#), 216 | Study design, Outcome
926 | Gurkan, F.,Davutog Lu, M.,Bilici, M.,Sincar, N.,Haspolat, K. (2002). Pulmonary functions in atopic and nonatopic asthmatic children Allergol Immunopathol (Madr), 30(2), 70-3 | Study design, Participant health
927 | Gurkan, F.,Davutoglu, M.,Bilici, M.,Dagli, A.,Haspolat, K. (2002). Asthmatic children and risk factors at a province in the southeast of Turkey Allergol Immunopathol (Madr), 30(1), 25-9 | Study design
928 | Gurnida, D. A.,Rowan, A. M.,Idjradinata, P.,Muchtadi, D.,Sekarwana, N. (2012). Association of complex lipids containing gangliosides with cognitive development of 6-month-old infants Early Hum Dev, 88(8), 595-601 | Country
929 | Gurwith, M.,Wenman, W.,Gurwith, D.,Brunton, J.,Feltham, S.,Greenberg, H. (1983). Diarrhea among infants and young children in Canada: a longitudinal study in three northern communities J Infect Dis, 147(4), 685-92 | Size of study groups, Intervention/exposure
930 | Gurwith, M.,Wenman, W.,Hinde, D.,Feltham, S.,Greenberg, H. (1981). A prospective study of rotavirus infection in infants and young children J Infect Dis, 144(3), 218-24 | Size of study groups
931 | Gustafsson, D.,Lowhagen, T.,Andersson, K. (1992). Risk of developing atopic disease after early feeding with cows’ milk based formula Arch Dis Child, 67(8), 1008-10 | Intervention/exposure
932 | Gustafsson, P. A.,Duchen, K.,Birberg, U.,Karlsson, T. (2004). Breastfeeding, very long polyunsaturated fatty acids (PUFA) and IQ at 6 1/2 years of age Acta Paediatr, 93(10), 1280-7 | Outcome
933 | Guxens, M.,Aguilera, I.,Ballester, F.,Estarlich, M.,Fernandez-Somoano, A.,Lertxundi, A.,Lertxundi, N.,Mendez, M. A.,Tardon, A.,Vrijheid, M.,Sunyer, J. (2012). Prenatal exposure to residential air pollution and infant mental development: modulation by antioxidants and detoxification factors Environ Health Perspect, 120(1), 144-9 | Outcome
934 | Guxens, M.,Mendez, M. A.,Molto-Puigmarti, C.,Julvez, J.,Garcia-Esteban, R.,Forns, J.,Ferrer, M.,Vrijheid, M.,Lopez-Sabater, M. C.,Sunyer, J. (2011). Breastfeeding, long-chain polyunsaturated fatty acids in colostrum, and infant mental development Pediatrics, 128(4), e880-9 | Outcome
935 | Habibzadeh, H.,Jafarizadeh, H.,Didarloo, A. (2015). Determinants of failure to thrive (FTT) among infants aged 6-24 months: a case-control study J Prev Med Hyg, 56(4), E180-6 | Study design
936 | Habicht, J. P.,DaVanzo, J.,Butz, W. P. (1986). Does breastfeeding really save lives, or are apparent benefits due to biases? Am J Epidemiol, 123(2), 279-90 | Study design
937 | Habicht, J. P.,DaVanzo, J.,Butz, W. P. (1988). Mother’s milk and sewage: their interactive effects on infant mortality Pediatrics, 81(3), 456-61 | Study design
938 | Hackney, A. R. (1990). Breast feeding Am J Nurs, 90(12), 70 | Study design
939 | Haddad, M. B.,Porucznik, C. A.,Joyce, K. E.,De, A. K.,Pavia, A. T.,Rolfs, R. T.,Byington, C. L. (2008). Risk factors for pediatric invasive pneumococcal disease in the Intermountain West, 1996-2002 Ann Epidemiol, 18(2), 139-46 | Intervention/exposure
940 | Haider, S. J.,Chang, L. V.,Bolton, T. A.,Gold, J. G.,Olson, B. H. (2014). An evaluation of the effects of a breastfeeding support program on health outcomes Health Serv Res, 49(6), 2017-34 | Intervention/exposure, Outcome
941 | Haines, M. R.,Kintner, H. J. (2008). “Can breast feeding help you in later life? Evidence from German military heights in the early 20th century” Econ Hum Biol, 6(3), 420-30 | Study design, Intervention/exposure
942 | Hakansson, A.,Carlsson, B. (1992). Maternal cigarette smoking, breast-feeding, and respiratory tract infections in infancy. A population-based cohort study Scand J Prim Health Care, 10(1), 60-5 | Study design, Outcome
943 | Halchak, B. (1982). The Oxford lactation study J Nurse Midwifery, 27(5), 34-6 | Intervention/exposure, Outcome
944 | Halken, S. (2004). What causes allergy and asthma? The role of dietary factors Pediatr Pulmonol Suppl, 26(#issue#), 223-4 | Study design
945 | Halken, S.,Hansen, K. S.,Jacobsen, H. P.,Estmann, A.,Faelling, A. E.,Hansen, L. G.,Kier, S. R.,Lassen, K.,Lintrup, M.,Mortensen, S.,Ibsen, K. K.,Osterballe, O.,Host, A. (2000). Comparison of a partially hydrolyzed infant formula with two extensively hydrolyzed formulas for allergy prevention: a prospective, randomized study Pediatr Allergy Immunol, 11(3), 149-61 | Intervention/exposure
946 | Halken, S.,Host, A.,Hansen, L. G.,Osterballe, O. (1992). Effect of an allergy prevention programme on incidence of atopic symptoms in infancy. A prospective study of 159 “high-risk” infants Allergy, 47(5), 545-53 | Study design, Intervention/exposure
947 | Halken, S.,Host, A.,Hansen, L. G.,Osterballe, O. (1993). Preventive effect of feeding high-risk infants a casein hydrolysate formula or an ultrafiltrated whey hydrolysate formula. A prospective, randomized, comparative clinical study Pediatr Allergy Immunol, 4(4), 173-81 | Size of study groups, Intervention/exposure
948 | Halken, S.,Host, A.,Husby, S.,Hansen, L. G.,Osterballe, O.,Nyboe, J. (1991). Recurrent wheezing in relation to environmental risk factors in infancy. A prospective study of 276 infants Allergy, 46(7), 507-14 | Outcome
949 | Hall, K.,Frederiksen, B.,Rewers, M.,Norris, J. M. (2015). Daycare attendance, breastfeeding, and the development of type 1 diabetes: the diabetes autoimmunity study in the young Biomed Res Int, 2015(#issue#), 203947 | Outcome
950 | Hallonsten, A. L.,Wendt, L. K.,Mejare, I.,Birkhed, D.,Hakansson, C.,Lindvall, A. M.,Edwardsson, S.,Koch, G. (1995). Dental caries and prolonged breast-feeding in 18-month-old Swedish children Int J Paediatr Dent, 5(3), 149-55 | Study design
951 | Hambraeus, L. (1982). The significance of mother’s milk and breast-feeding for development and later life Bibl Nutr Dieta, #volume#(31), 1-16 | Study design
952 | Hamburger, R. N.,Heller, S.,Mellon, M. H.,O’Connor, R. D.,Zeiger, R. S. (1983). Current status of the clinical and immunologic consequences of a prototype allergic disease prevention program Ann Allergy, 51(2 Pt 2), 281-90 | Study design, Intervention/exposure
953 | Hamilton, J. J.,Synnes, A.,Innis, S. M. (1992). Plasma cholesterol and lathosterol levels in term infants in the early neonatal period Pediatr Res, 31(4 Pt 1), 396-400 | Size of study groups
954 | Hamilton, J. R. (1985). Viral diarrhea Pediatr Ann, 14(1), 25-8 | Study design
955 | Han, D. H.,Ahn, J. C.,Mun, S. J.,Park, S. K.,Oh, S. Y.,Rhee, C. S. (2015). Novel risk factors for allergic rhinitis in Korean elementary school children: ARCO-kids phase II in a community Allergy, Asthma and Immunology Research, 7(3), 234-240 | Study design
956 | Han, D. Y.,Fraser, A. G.,Dryland, P.,Ferguson, L. R. (2010). Environmental factors in the development of chronic inflammation: a case-control study on risk factors for Crohn’s disease within New Zealand Mutat Res, 690(1-2), 116-22 | Study design
957 | Han, Y. S.,Park, H. Y.,Ahn, K. M.,Lee, J. S.,Choi, H. M.,Lee, S. I. (2003). Short-term effect of partially hydrolyzed formula on the prevention of development of atopic dermatitis in infants at high risk J Korean Med Sci, 18(4), 547-51 | Size of study groups
958 | Han, Y.,Chung, S. J.,Kim, J.,Ahn, K.,Lee, S. I. (2009). High sensitization rate to food allergens in breastfed infants with atopic dermatitis Ann Allergy Asthma Immunol, 103(4), 332-6 | Study design, Outcome
959 | Hancox, R. J.,Stewart, A. W.,Braithwaite, I.,Beasley, R.,Murphy, R.,Mitchell, E. A. (2015). Association between breastfeeding and body mass index at age 6-7 years in an international survey Pediatr Obes, 10(4), 283-7 | Study design
960 | Hanicar, B.,Mandic, Z.,Pavic, R. (2009). Exclusive breastfeeding and growth in Croatian infants--comparison to the WHO child growth standards and to the NCHS growth references Coll Antropol, 33(3), 735-41 | Outcome
961 | Hanning, R. M.,Paes, B.,Atkinson, S. A. (1992). Protein metabolism and growth of term infants in response to a reduced-protein, 40:60 whey: casein formula with added tryptophan Am J Clin Nutr, 56(6), 1004-11 | Outcome
962 | Hansen, K. (2015). The Power of Nutrition and the Power of Breastfeeding Breastfeed Med, 10(8), 385-8 | Study design
963 | Hansen, T. S.,Jess, T.,Vind, I.,Elkjaer, M.,Nielsen, M. F.,Gamborg, M.,Munkholm, P. (2011). Environmental factors in inflammatory bowel disease: a case-control study based on a Danish inception cohort J Crohns Colitis, 5(6), 577-84 | Outcome
964 | Hanson, L. A.,Ashraf, R.,Zaman, S.,Karlberg, J.,Lindblad, B. S.,Jalil, F. (1994). Breast feeding is a natural contraceptive and prevents disease and death in infants, linking infant mortality and birth rates Acta Paediatr, 83(1), 3-6 | Study design
965 | Hanson, L. A.,Jalil, F.,Ashraf, R.,Bernini, S.,Carlsson, B.,Cruz, J. R.,Gonzalez, T.,Hahn-Zoric, M.,Mellander, L.,Minoli, Y.,et al, (1991). Characteristics of human milk antibodies and their effect in relation to the epidemiology of breastfeeding and infections in a developing country Adv Exp Med Biol, 310(#issue#), 1-15 | Country
966 | Happ B (1986). Infants receive nutrition from human breast milk NAACOG Newsl, 13(#issue#), 1, 12-3 | Study design
967 | Haq, M. E.,Begum, K.,Muttalib, M. A.,Shahidullah, M. (1985). Prevalence of caries in urban children and its relation to feeding pattern Bangladesh Med Res Counc Bull, 11(2), 55-63 | Country
968 | Hardell, L.,Dreifaldt, A. C. (2001). Breast-feeding duration and the risk of malignant diseases in childhood in Sweden Eur J Clin Nutr, 55(3), 179-85 | Intervention/exposure
969 | Hardy, E. E.,Vichi, A. M.,Sarmento, R. C.,Moreira, L. E.,Bosqueiro, C. M. (1982). Breastfeeding promotion: effect of an educational program in Brazil Stud Fam Plann, 13(3), 79-86 | Outcome
970 | Harkin, T. (2011). Wellness and disease prevention begins at birth: the critically important role of breastfeeding Breastfeed Med, 6(#issue#), 245-6 | Study design
971 | Harland, B. F.,Smith, S. A.,Ellis, R.,O’Brien, R.,Morris, E. R. (1992). Comparison of the nutrient intakes of blacks, Siouan Indians, and whites in Columbus County, North Carolina Journal of the American Dietetic Association, 92(3), 348-350 | Study design, Outcome
972 | Harris, J. M.,Cullinan, P.,Williams, H. C.,Mills, P.,Moffat, S.,White, C.,Newman Taylor, A. J. (2001). Environmental associations with eczema in early life Br J Dermatol, 144(4), 795-802 | Outcome
973 | Harris, M. C.,Kolski, G. B.,Campbell, D. E.,Deuber, C.,Marcus, M.,Douglas, S. D. (1989). Ontogeny of the antibody response to cow milk proteins Ann Allergy, 63(5), 439-43 | Size of study groups
974 | Harrison, G. G.,Graver, E. J.,Vargas, M.,Churella, H. R.,Paule, C. L. (1987). Growth and adiposity of term infants fed whey-predominant or casein-predominant formulas or human milk J Pediatr Gastroenterol Nutr, 6(5), 739-47 | Size of study groups
975 | Harrison, R.,Wong, T.,Ewan, C.,Contreras, B.,Phung, Y. (1997). Feeding practices and dental caries in an urban Canadian population of Vietnamese preschool children ASDC J Dent Child, 64(2), 112-7 | Study design
976 | Harsten, G.,Prellner, K.,Heldrup, J.,Kalm, O.,Kornfalt, R. (1989). Recurrent acute otitis media. A prospective study of children during the first three years of life Acta Otolaryngol, 107(1-2), 111-9 | Size of study groups
977 | Hart, S.,Boylan, L. M.,Carroll, S.,Musick, Y. A.,Lampe, R. M. (2003). Brief report: breast-fed one-week-olds demonstrate superior neurobehavioral organization J Pediatr Psychol, 28(8), 529-34 | Outcome
978 | Hartley, A. L.,Birch, J. M.,McKinney, P. A.,Blair, V.,Teare, M. D.,Carrette, J.,Mann, J. R.,Stiller, C. A.,Draper, G. J.,Johnston, H. E.,et al, (1988). The Inter-Regional Epidemiological Study of Childhood Cancer (IRESCC): past medical history in children with cancer J Epidemiol Community Health, 42(3), 235-42 | Outcome
979 | Harvey, N. C.,Robinson, S. M.,Crozier, S. R.,Marriott, L. D.,Gale, C. R.,Cole, Z. A.,Inskip, H. M.,Godfrey, K. M.,Cooper, C. (2009). Breast-feeding and adherence to infant feeding guidelines do not influence bone mass at age 4 years Br J Nutr, 102(6), 915-20 | Outcome
980 | Haschke, F.,van’t Hof, M. A. (2000). Euro-Growth references for breast-fed boys and girls: influence of breast-feeding and solids on growth until 36 months of age. Euro-Growth Study Group J Pediatr Gastroenterol Nutr, 31 Suppl 1(#issue#), S60-71 | Intervention/exposure
981 | Haschke, F.,Vanura, H.,Male, C.,Owen, G.,Pietschnig, B.,Schuster, E.,Krobath, E.,Huemer, C. (1993). Iron nutrition and growth of breast- and formula-fed infants during the first 9 months of life J Pediatr Gastroenterol Nutr, 16(2), 151-6 | Size of study groups
982 | Haschke, F.,Ziegler, E. E.,Grathwohl, D. (2014). Fast growth of infants of overweight mothers: Can it be slowed down? Annals of Nutrition and Metabolism, 64(#issue#), 19-24 | Intervention/exposure
983 | Hashim SA (1983). Dietary fats and adipose tissue fatty acid composition Prev Med, 12(#issue#), 854-67 | Study design
984 | Hasselbalch, H.,Jeppesen, D. L.,Ersboll, A. K.,Engelmann, M. D.,Nielsen, M. B. (1997). Thymus size evaluated by sonography. A longitudinal study on infants during the first year of life Acta Radiol, 38(2), 222-7 | Size of study groups, Outcome
985 | Hassiotou, F.,Geddes, D. T. (2014). Programming of appetite control during breastfeeding as a preventative strategy against the obesity epidemic J Hum Lact, 30(2), 136-42 | Study design
986 | Hatano, S.,Aihara, K.,Nishi, Y.,Usui, T. (1985). Trace elements (copper, zinc, manganese, and selenium) in plasma and erythrocytes in relation to dietary intake during infancy J Pediatr Gastroenterol Nutr, 4(1), 87-92 | Size of study groups
987 | Hathcock, A.,Krause, K.,Viera, A. J.,Fuemmeler, B. F.,Lovelady, C.,Ostbye, T. (2014). Satiety responsiveness and the relationship between breastfeeding and weight status of toddlers of overweight and obese women Matern Child Health J, 18(4), 1023-30 | Study design
988 | Hattab, F. N.,Al-Omari, M. A.,Angmar-Mansson, B.,Daoud, N. (1999). The prevalence of nursing caries in one-to-four-year-old children in Jordan ASDC J Dent Child, 66(1), 53-8 | Study design
989 | Hauck, F. R.,Herman, S. M.,Donovan, M.,Iyasu, S.,Merrick Moore, C.,Donoghue, E.,Kirschner, R. H.,Willinger, M. (2003). Sleep environment and the risk of sudden infant death syndrome in an urban population: the Chicago Infant Mortality Study Pediatrics, 111(5 Pt 2), 1207-14 | Outcome
990 | Hawkes, J. S.,Gibson, R. A.,Roberton, D.,Makrides, M. (2006). Effect of dietary nucleotide supplementation on growth and immune function in term infants: a randomized controlled trial Eur J Clin Nutr, 60(2), 254-64 | Outcome
991 | Hawkins, S. S.,Cole, T. J.,Law, C. (2009). An ecological systems approach to examining risk factors for early childhood overweight: findings from the UK Millennium Cohort Study J Epidemiol Community Health, 63(2), 147-55 | Outcome
992 | Hawley, N. L.,Johnson, W.,Nu’usolia, O.,McGarvey, S. T. (2014). The contribution of feeding mode to obesogenic growth trajectories in American Samoan infants Pediatr Obes, 9(1), e1-e13 | Intervention/exposure
993 | Hay, A. E.,Campbell, C. M. A. (2004). Volunteer counsellors for supporting breast feeding…Graffy J, Taylor J, Williams A et al Randomised controlled trial of support from volunteer counsellors for mothers considering breast feeding. BMJ 2004;328:26. (3 January) BMJ: British Medical Journal (International Edition), 328(7435), 349-349 1p | Study design
994 | Hay, D. F.,Pawlby, S.,Sharp, D.,Asten, P.,Mills, A.,Kumar, R. (2001). Intellectual problems shown by 11-year-old children whose mothers had postnatal depression J Child Psychol Psychiatry, 42(7), 871-89 | Outcome
995 | Hay, G.,Clausen, T.,Whitelaw, A.,Trygg, K.,Johnston, C.,Henriksen, T.,Refsum, H. (2010). Maternal folate and cobalamin status predicts vitamin status in newborns and 6-month-old infants J Nutr, 140(3), 557-64 | Intervention/exposure
996 | Hay, G.,Johnston, C.,Whitelaw, A.,Trygg, K.,Refsum, H. (2008). Folate and cobalamin status in relation to breastfeeding and weaning in healthy infants Am J Clin Nutr, 88(1), 105-14 | Study design, Intervention/exposure
997 | Hayatbakhsh, M. R.,O’Callaghan M, J.,Bor, W.,Williams, G. M.,Najman, J. M. (2012). Association of breastfeeding and adolescents’ psychopathology: A large prospective study Breastfeeding Medicine, 7(6), 480-486 | Outcome
998 | Hayes, K. C.,Pronczuk, A.,Wood, R. A.,Guy, D. G. (1992). Modulation of infant formula fat profile alters the low-density lipoprotein/high-density lipoprotein ratio and plasma fatty acid distribution relative to those with breast-feeding J Pediatr, 120(4 Pt 2), S109-16 | Size of study groups
999 | Hayosh, O.,Mandel, D.,Mimouni, F. B.,Lahat, S.,Marom, R.,Lubetzky, R. (2015). Prolonged duration of breastfeeding does not affect lipid profile in adulthood Breastfeed Med, 10(4), 218-21 | Study design
1000 | Hearst, Mary O.,Martin, Lauren,Rafdal, Brooke H.,Robinson, Ronel,McConnell, Scott R. (2013). Early childhood development and obesity risk-factors in a multi-ethnic, low-income community: Feasibility of the ‘Five Hundred under Five’ social determinants of health pilot study Health Education Journal, 72(2), 203-215 13p | Study design
1001 | Heath, A. L.,Tuttle, C. R.,Simons, M. S.,Cleghorn, C. L.,Parnell, W. R. (2002). Longitudinal study of diet and iron deficiency anaemia in infants during the first two years of life Asia Pac J Clin Nutr, 11(4), 251-7 | Size of study groups, Intervention/exposure
1002 | Hedstrom, M. (1982). Breastfeeding and Amningshjalpen in Sweden J Trop Pediatr, 28(3), 113-5 | Study design
1003 | Hegde CV,Anand RK (1987). Bowel pattern and weight gain in breastfed infants Indian Pediatr, 24(#issue#), 859-64 | Country
1004 | Heikkila, K.,Kelly, Y.,Renfrew, M. J.,Sacker, A.,Quigley, M. A. (2014). Breastfeeding and educational achievement at age 5 Matern Child Nutr, 10(1), 92-101 | Outcome
1005 | Heikkilä, K.,Sacker, A.,Kelly, Y.,Renfrew, M. J.,Quigley, M. A. (2010). 012 Breast feeding and behavioural development in children: findings from the Millennium Cohort Study Journal of Epidemiology & Community Health, 64(#issue#), A5-A5 1p | Publication status
1006 | Heikkila, K.,Sacker, A.,Kelly, Y.,Renfrew, M. J.,Quigley, M. A. (2011). Breast feeding and child behaviour in the Millennium Cohort Study Arch Dis Child, 96(7), 635-42 | Outcome
1007 | Heine, W.,Lapsien, C. (1982). Influence of early breast milk and formula feeding on body weight in children born in Rostock since 1945 Bibl Nutr Dieta, #volume#(31), 17-8 | Study design, Intervention/exposure
1008 | Heiner, D. C. (1984). Modern research relating to food allergy and its implications--introduction Clin Rev Allergy, 2(1), 1-5 | Study design
1009 | Heinig, J.,Ishii, K. (2004). Exclusive breastfeeding: isn’t some breastfeeding good enough? J Hum Lact, 20(4), 423-4 | Study design
1010 | Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B.,Dewey, K. G. (1993). Energy and protein intakes of breast-fed and formula-fed infants during the first year of life and their association with growth velocity: the DARLING Study Am J Clin Nutr, 58(2), 152-61 | Intervention/exposure
1011 | Heinig, M. J.,Nommsen, L. A.,Peerson, J. M.,Lonnerdal, B.,Dewey, K. G. (1993). Intake and growth of breast-fed and formula-fed infants in relation to the timing of introduction of complementary foods: the DARLING study. Davis Area Research on Lactation, Infant Nutrition and Growth Acta Paediatr, 82(12), 999-1006 | Intervention/exposure
1012 | Heinonen, K.,Raikkonen, K.,Pesonen, A. K.,Andersson, S.,Kajantie, E.,Eriksson, J. G.,Wolke, D.,Lano, A. (2011). Longitudinal study of smoking cessation before pregnancy and children’s cognitive abilities at 56 months of age Early Hum Dev, 87(5), 353-9 | Participant health, Intervention/exposure
1013 | Hemalatha, P.,Bhaskaram, P.,Kumar, P. A.,Khan, M. M.,Islam, M. A. (1997). Zinc status of breastfed and formula-fed infants of different gestational ages J Trop Pediatr, 43(1), 52-4 | Country, Size of study group
1014 | Henry, F. J.,Bartholomew, R. K. (1990). Epidemiology and transmission of rotavirus infections and diarrhoea in St. Lucia, West Indies West Indian Med J, 39(4), 205-12 | Study design, Intervention/exposure
1015 | Heppe, D. H. M.,Kiefte-De Jong, J. C.,Durmuş, B.,Moll, H. A.,Raat, H.,Hofman, A.,Jaddoe, V. W. V. (2013). Parental, fetal, and infant risk factors for preschool overweight: The Generation R Study Pediatric Research, 73(1), 120-127 | Outcome
1016 | Hepworth, S. J.,Law, G. R.,Lawlor, D. A.,McKinney, P. A. (2010). Early life patterns of common infection: a latent class analysis Eur J Epidemiol, 25(12), 875-83 | Outcome
1017 | Herba, C. M.,Roza, S.,Govaert, P.,Hofman, A.,Jaddoe, V.,Verhulst, F. C.,Tiemeier, H. (2013). Breastfeeding and early brain development: the Generation R study Matern Child Nutr, 9(3), 332-49 | Outcome
1018 | Heresi, G.,Pizarro, F.,Olivares, M.,Cayazzo, M.,Hertrampf, E.,Walter, T.,Murphy, J. R.,Stekel, A. (1995). Effect of supplementation with an iron-fortified milk on incidence of diarrhea and respiratory infection in urban-resident infants Scand J Infect Dis, 27(4), 385-9 | Outcome
1019 | Hernell, O. (1990). The requirements and utilization of dietary fatty acids in the newborn infant Acta Paediatr Scand Suppl, 365(#issue#), 20-7 | Study design
1020 | Hernell, O.,Lonnerdal, B. (2002). Iron status of infants fed low-iron formula: no effect of added bovine lactoferrin or nucleotides Am J Clin Nutr, 76(4), 858-64 | Size of study groups, Intervention/exposure
1021 | Hernell, O.,Lonnerdal, B. (2003). Nutritional evaluation of protein hydrolysate formulas in healthy term infants: plasma amino acids, hematology, and trace elements Am J Clin Nutr, 78(2), 296-301 | Size of study groups
1022 | Hertrampf, E.,Cayazzo, M.,Pizarro, F.,Stekel, A. (1986). Bioavailability of iron in soy-based formula and its effect on iron nutriture in infancy Pediatrics, 78(4), 640-5 | Intervention/exposure
1023 | Hesselmar, B.,Saalman, R.,Rudin, A.,Adlerberth, I.,Wold, A. E. (2010). Early fish introduction is associated with less eczema, but not sensitization, in infants Acta Paediatrica, International Journal of Paediatrics, 99(12), 1861-1867 | Outcome
1024 | Hetzner, N. M.,Razza, R. A.,Malone, L. M.,Brooks-Gunn, J. (2009). Associations among feeding behaviors during infancy and child illness at two years Matern Child Health J, 13(6), 795-805 | Outcome
1025 | Hide DW,Guyer BM (1983). Cows milk intolerance in Isle of Wight infants Br J Clin Pract, 37(#issue#), 285-7 | Outcome, Size of study groups
1026 | Hide, D. W. (1980). Aspects of nutrition: Isle of Wight infant feeding survey Health Visit, 53(2), 43 | Study design
1027 | Hide, D. W. (1991). The clinical expression of allergy in breast-fed infants Adv Exp Med Biol, 310(#issue#), 475-80 | Study design
1028 | Hide, D. W.,Guyer, B. M. (1981). Clinical manifestations of allergy related to breast and cows’ milk feeding Arch Dis Child, 56(3), 172-5 | Intervention/exposure
1029 | Hide, D. W.,Guyer, B. M. (1985). Clinical manifestations of allergy related to breast- and cow’s milk-feeding Pediatrics, 76(6), 973-5 | Intervention/exposure
1030 | Hide, D. W.,Matthews, S.,Matthews, L.,Stevens, M.,Ridout, S.,Twiselton, R.,Gant, C.,Arshad, S. H. (1994). Effect of allergen avoidance in infancy on allergic manifestations at age two years J Allergy Clin Immunol, 93(5), 842-6 | Intervention/exposure
1031 | Hide, D. W.,Matthews, S.,Tariq, S.,Arshad, S. H. (1996). Allergen avoidance in infancy and allergy at 4 years of age Allergy, 51(2), 89-93 | Intervention/exposure
1032 | Higashi, A.,Ikeda, T.,Uehara, I.,Matsuda, I. (1982). Effect of low-content zinc and copper formula on infant nutrition Eur J Pediatr, 138(3), 237-40 | Size of study groups
1033 | Highet, A. R.,Berry, A. M.,Bettelheim, K. A.,Goldwater, P. N. (2014). Gut microbiome in sudden infant death syndrome (SIDS) differs from that in healthy comparison babies and offers an explanation for the risk factor of prone position Int J Med Microbiol, 304(5-6), 735-41 | Intervention/exposure, Outcome
1034 | Hijazi, S. S.,Abulaban, A.,Waterlow, J. C. (1989). The duration for which exclusive breast-feeding is adequate. A study in Jordan Acta Paediatr Scand, 78(1), 23-8 | Intervention/exposure
1035 | Hiley, C. M.,Morley, C. J. (1996). Risk factors for sudden infant death syndrome: further change in 1992-3 BMJ, 312(7043), 1397-8 | Study design
1036 | Hill, D. J.,Hosking, C. S. (1993). Preventing childhood allergy Med J Aust, 158(6), 367-9 | Study design
1037 | Hillemeier, M. M.,Landale, N. S.,Oropesa, R. S. (2015). Asthma in US Mexican-Origin Children in Early Childhood: Differences in Risk and Protective Factors by Parental Nativity Acad Pediatr, 15(4), 421-9 | Outcome
1038 | Hillman, L. S. (1988). Bone mineral content in term infants fed human milk, cow milk-based formula, or soy-based formula J Pediatr, 113(1 Pt 2), 208-12 | Size of study groups
1039 | Hillman, L. S.,Chow, W.,Salmons, S. S.,Weaver, E.,Erickson, M.,Hansen, J. (1988). Vitamin D metabolism, mineral homeostasis, and bone mineralization in term infants fed human milk, cow milk-based formula, or soy-based formula J Pediatr, 112(6), 864-74 | Size of study groups
1040 | Hirota, T.,Nara, M.,Ohguri, M.,Manago, E.,Hirota, K. (1992). Effect of diet and lifestyle on bone mass in Asian young women Am J Clin Nutr, 55(6), 1168-73 | Study design
1041 | Hitchcock, N. E.,Coy, J. F. (1989). The growth of healthy Australian infants in relation to infant feeding and social group Med J Aust, 150(6), 306-8, 310-1 | Outcome
1042 | Hitchcock, N. E.,Gracey, M.,Gilmour, A. I. (1985). The growth of breast fed and artificially fed infants from birth to twelve months Acta Paediatr Scand, 74(2), 240-5 | Outcome
1043 | Hitchcock, N. E.,Gracey, M.,Owles, E. N. (1981). Growth of healthy breast-fed infants in the first six months Lancet, 2(8237), 64-5 | Study design, Intervention/exposure
1044 | Hitchcock, N. E.,McGuiness, D.,Gracey, M. (1982). Growth and feeding practices of Western Australian infants Med J Aust, 1(9), 372-6 | Outcome
1045 | Hitchcock, N. E.,Owles, E. N.,Gracey, M. (1981). Breast feeding and growth of healthy infants Med J Aust, 2(10), 536-7 | Study design
1046 | Hlavaty, T.,Toth, J.,Koller, T.,Krajcovicova, A.,Oravcova, S.,Zelinkova, Z.,Huorka, M. (2013). Smoking, breastfeeding, physical inactivity, contact with animals, and size of the family influence the risk of inflammatory bowel disease: A Slovak case–control study United European Gastroenterology Journal, 1(2), 109-119 | Outcome
1047 | Hoffhines, H.,Whaley, K. D.,Blackett, P. R.,Palumbo, K.,Campbell-Sternloff, D.,Glore, S.,Lee, E. T. (2014). Early childhood nutrition in an American Indian community: educational strategy for obesity prevention J Okla State Med Assoc, 107(2), 55-9 | Outcome
1048 | Hoffman, D. R.,Birch, E. E.,Birch, D. G.,Uauy, R.,Castaneda, Y. S.,Lapus, M. G.,Wheaton, D. H. (2000). Impact of early dietary intake and blood lipid composition of long-chain polyunsaturated fatty acids on later visual development J Pediatr Gastroenterol Nutr, 31(5), 540-53 | Intervention/exposure
1049 | Hoffman, D. R.,Birch, E. E.,Castaneda, Y. S.,Fawcett, S. L.,Birch, D. G.,Uauy, R. (2001). Dietary docosahexaenoic acid (DHA) and visual maturation in the post-weaning term infant Iovs, 42(#issue#), ARVO Abstract 656 | Publication status
1050 | Hoffman, D. R.,Birch, E. E.,Castaneda, Y. S.,Fawcett, S. L.,Wheaton, D. H.,Birch, D. G.,Uauy, R. (2003). Visual function in breast-fed term infants weaned to formula with or without long-chain polyunsaturates at 4 to 6 months: a randomized clinical trial J Pediatr, 142(6), 669-77 | Outcome
1051 | Hoffman, D. R.,Wheaton, D. K.,James, K. J.,Tuazon, M.,Diersen-Schade, D. A.,Harris, C. L.,Stolz, S.,Berseth, C. L. (2006). Docosahexaenoic acid in red blood cells of term infants receiving two levels of long-chain polyunsaturated fatty acids J Pediatr Gastroenterol Nutr, 42(3), 287-92 | Intervention/exposure
1052 | Hoffman, D.,Birch, E.,Birch, D.,Uauy, R.,Castaneda, Y.,Wheaton, D. (1996). Red blood cell (rbc) fatty acid profiles in term infants fed formulas enriched with long-chain polyunsaturates (lcp) Iovs, 37(#issue#), ARVO Abstract 3693 | Study design, Intervention/exposure
1053 | Hoffmans, M. D.,Obermann-de Boer, G. L.,Florack, E. I.,van Kampen-Donker, M.,Kromhout, D. (1988). Determinants of growth during early infancy Hum Biol, 60(2), 237-49 | Outcome
1054 | Hofvander Y,Hillervik C (1995). Breast-feeding in Swedish hospitals World Health Forum, 16(#issue#), 95-9 | Study design, Outcome
1055 | Hogendorf, A.,Stanczyk-Przyluska, A.,Sieniwicz-Luzenczyk, K.,Wiszniewska, M.,Arendarczyk, J.,Banasik, M.,Fendler, W.,Kowalski, M.,Zeman, K. (2013). Is there any association between secretory IgA and lactoferrin concentration in mature human milk and food allergy in breastfed children Med Wieku Rozwoj, 17(1), 47-52 | Intervention/exposure
1056 | Hokama, T. (1993). A study of the hemoglobin levels in breast-fed infants in one village of Okinawa prefecture Acta Paediatr Jpn, 35(2), 138-40 | Size of study groups
1057 | Hokama, T. (1993). Levels of serum ferritin and total body iron among infants with different feeding regimens Acta Paediatr Jpn, 35(4), 298-301 | Study design, Size of study groups
1058 | Hokama, T.,Sakamoto, R.,Yara, A.,Asato, Y.,Takamine, F.,Itokazu, K. (1999). Incidence of Haemophilus influenzae in the throats of healthy infants with different feeding methods Pediatr Int, 41(3), 277-80 | Study design
1059 | Holberg, C. J.,Wright, A. L.,Martinez, F. D.,Ray, C. G.,Taussig, L. M.,Lebowitz, M. D. (1991). Risk factors for respiratory syncytial virus-associated lower respiratory illnesses in the first year of life Am J Epidemiol, 133(11), 1135-51 | Intervention/exposure
1060 | Holland, B. (1987). Breast-feeding, social variables, and infant mortality: a hazards model analysis of the case of Malaysia Soc Biol, 34(1-2), 78-93 | Study design
1061 | Holland, B. (1987). The validity of retrospective breast-feeding-duration data: an illustrative analysis of data quality in the Malaysian Family Life Survey Hum Biol, 59(3), 477-87 | Study design
1062 | Hollen, L. I.,Din, Zu,Jones, L. R.,Emond, A. M.,Emmett, P. (2014). Are diet and feeding behaviours associated with the onset of and recovery from slow weight gain in early infancy? Br J Nutr, 111(9), 1696-704 | Intervention/exposure
1063 | Hollis, B. W.,Wagner, C. L.,Howard, C. R.,Ebeling, M.,Shary, J. R.,Smith, P. G.,Taylor, S. N.,Morella, K.,Lawrence, R. A.,Hulsey, T. C. (2015). Maternal Versus Infant Vitamin D Supplementation During Lactation: A Randomized Controlled Trial Pediatrics, 136(4), 625-34 | Intervention/exposure
1064 | Holm, A. K.,Andersson, R. (1982). Enamel mineralization disturbances in 12-year-old children with known early exposure to fluorides Community Dent Oral Epidemiol, 10(6), 335-9 | Intervention/exposure, Outcome
1065 | Holman, D. J.,Yamaguchi, K. (2005). Longitudinal analysis of deciduous tooth emergence: IV. Covariate effects in Japanese children Am J Phys Anthropol, 126(3), 352-8 | Intervention/exposure
1066 | Holme, A.,MacArthur, C.,Lancashire, R. (2010). The effects of breastfeeding on cognitive and neurological development of children at 9 years Child Care Health Dev, 36(4), 583-90 | Study design
1067 | Holmes, G. E.,Hassanein, K. M.,Miller, H. C. (1983). Factors associated with infections among breast-fed babies and babies fed proprietary milks Pediatrics, 72(3), 300-6 | Intervention/exposure
1068 | Holmes, V. A.,Cardwell, C.,McKinley, M. C.,Young, I. S.,Murray, L. J.,Boreham, C. A.,Woodside, J. V. (2010). Association between breast-feeding and anthropometry and CVD risk factor status in adolescence and young adulthood: the Young Hearts Project, Northern Ireland Public Health Nutr, 13(6), 771-8 | Intervention/exposure
1069 | Holscher, H. D.,Czerkies, L. A.,Cekola, P.,Litov, R.,Benbow, M.,Santema, S.,Alexander, D. D.,Perez, V.,Sun, S.,Saavedra, J. M.,Tappenden, K. A. (2012). Bifidobacterium lactis Bb12 enhances intestinal antibody response in formula-fed infants: a randomized, double-blind, controlled trial JPEN J Parenter Enteral Nutr, 36(1 Suppl), 106S-17S | Intervention/exposure, Outcome
1070 | Holt, R. D.,Joels, D.,Winter, G. B. (1982). Caries in pre-school children. The Camden study Br Dent J, 153(3), 107-9 | Study design
1071 | Holt, R. D.,Winter, G. B.,Downer, M. C.,Bellis, W. J.,Hay, I. S. (1996). Caries in pre-school children in Camden 1993/94 Br Dent J, 181(11-12), 405-10 | Study design
1072 | Hon, K. L. E.,Leung, T. F.,Kam, W. Y. C.,Lam, M. C. A.,Fok, T. F.,Ng, P. C. (2006). Dietary restriction and supplementation in children with atopic eczema Clinical and Experimental Dermatology, 31(2), 187-191 | Study design
1073 | Hong, L.,Levy, S. M.,Warren, J. J.,Broffitt, B. (2014). Infant breast-feeding and childhood caries: a nine-year study Pediatr Dent, 36(4), 342-7 | Outcome
1074 | Hong, X.,Wang, G.,Liu, X.,Kumar, R.,Tsai, H. J.,Arguelles, L.,Hao, K.,Pearson, C.,Ortiz, K.,Bonzagni, A.,Apollon, S.,Fu, L.,Caruso, D.,Pongracic, J. A.,Schleimer, R.,Holt, P. G.,Bauchner, H.,Wang, X. (2011). Gene polymorphisms, breast-feeding, and development of food sensitization in early childhood J Allergy Clin Immunol, 128(2), 374-81 e2 | Outcome
1075 | Hong, Z. Y.,Zhang, Y. W.,Xu, J. D.,Zhou, J. D.,Gao, X. L.,Liu, X. G.,Shi, Y. Y. (1992). Growth promoting effect of zinc supplementation in infants of high-risk pregnancies Chin Med J (Engl), 105(10), 844-8 | Size of study groups
1076 | Honorio, R. F.,Costa Monteiro Hadler, M. C. (2014). Factors associated with obesity in brazilian children enrolled in the school health program: a case-control study Nutr Hosp, 30(3), 526-34 | Study design
1077 | Hopkins, D.,Emmett, P.,Steer, C.,Rogers, I.,Noble, S.,Emond, A. (2007). Infant feeding in the second 6 months of life related to iron status: an observational study Arch Dis Child, 92(10), 850-4 | Intervention/exposure
1078 | Hopkins, D.,Steer, C. D.,Northstone, K.,Emmett, P. M. (2015). Effects on childhood body habitus of feeding large volumes of cow or formula milk compared with breastfeeding in the latter part of infancy Am J Clin Nutr, 102(5), 1096-103 | Intervention/exposure
1079 | Hopkinson, J. (2003). Is it possible for a breastfed baby to be overweight? J Hum Lact, 19(2), 189-90 | Study design
1080 | Hoppu, U.,Isolauri, E.,Koskinen, P.,Laitinen, K. (2013). Diet and blood lipids in 1-4 year-old children Nutr Metab Cardiovasc Dis, 23(10), 980-6 | Outcome
1081 | Hoppu, U.,Kalliomaki, M.,Isolauri, E. (2002). Cow’s milk allergy--a matter of fat Allergy, 57(1), 61-2 | Study design, Intervention/exposure
1082 | Horby Jorgensen, M.,Holmer, G.,Lund, P.,Hernell, O.,Michaelsen, K. F. (1998). Effect of formula supplemented with docosahexaenoic acid and gamma-linolenic acid on fatty acid status and visual acuity in term infants J Pediatr Gastroenterol Nutr, 26(4), 412-21 | Size of study groups, Intervention/exposure
1083 | Horst, C. H.,Obermann-de Boer, G. L.,Kromhout, D. (1987). Type of milk feeding and nutrient intake during infancy. The Leiden Pre-School Children Study Acta Paediatr Scand, 76(6), 865-71 | Study design, Outcome
1084 | Horta, B. L.,Bas, A.,Bhargava, S. K.,Fall, C. H.,Feranil, A.,de Kadt, J.,Martorell, R.,Richter, L. M.,Stein, A. D.,Victora, C. G. (2013). Infant feeding and school attainment in five cohorts from low- and middle-income countries PLoS One, 8(8), e71548 | Outcome
1085 | Horta, B. L.,Victora, C. G.,Lima, R. C.,Goncalves, H.,Guimaraes, B. E.,Barros, F. C. (2006). Breastfeeding duration and blood pressure among Brazilian adolescents Acta Paediatr, 95(3), 325-31 | Outcome
1086 | Horton, C. (2012). An overview of the NUTRIMENTHE project Nutrition Bulletin, 37(2), 152-156 5p | Study design
1087 | Horwood, L. J.,Fergusson, D. M. (1998). Breastfeeding and later cognitive and academic outcomes Pediatrics, 101(1), E9 | Outcome
1088 | Horwood, L. J.,Fergusson, D. M.,Shannon, F. T. (1985). Social and familial factors in the development of early childhood asthma Pediatrics, 75(5), 859-68 | Size of study groups, Intervention/exposure
1089 | Hosaka, M.,Asayama, K.,Staessen, J. A.,Ohkubo, T.,Hayashi, K.,Tatsuta, N.,Kurokawa, N.,Satoh, M.,Hashimoto, T.,Hirose, T.,Obara, T.,Metoki, H.,Inoue, R.,Kikuya, M.,Nakai, K.,Imai, Y.,Satoh, H. (2013). Breastfeeding leads to lower blood pressure in 7-year-old Japanese children: Tohoku Study of Child Development Hypertens Res, 36(2), 117-22 | Outcome
1090 | Hosseini, S. M.,Maracy, M. R.,Sarrafzade, S.,Kelishadi, R. (2014). Child weight growth trajectory and its determinants in a sample of Iranian children from birth until 2 years of age International Journal of Preventive Medicine, 5(3), 348-355 | Intervention/exposure
1091 | Host, A. (1991). Importance of the first meal on the development of cow’s milk allergy and intolerance Allergy Proc, 12(4), 227-32 | Outcome
1092 | Host, A.,Husby, S.,Osterballe, O. (1988). A prospective study of cow’s milk allergy in exclusively breast-fed infants. Incidence, pathogenetic role of early inadvertent exposure to cow’s milk formula, and characterization of bovine milk protein in human milk Acta Paediatr Scand, 77(5), 663-70 | Study design, Intervention/exposure
1093 | Houston M,Howie P,McNeilly A (1983). Nursing Mirror Midwifery Forum 4. Infant feeding Nurs Mirror, 156(#issue#), i-iv | Study design
1094 | Hovland, V.,Riiser, A.,Mowinckel, P.,Carlsen, K. H.,Lodrup Carlsen, K. C. (2015). Early risk factors for pubertal asthma Clin Exp Allergy, 45(1), 164-76 | Outcome
1095 | Howe, L. D.,Ellison-Loschmann, L.,Pearce, N.,Douwes, J.,Jeffreys, M.,Firestone, R. (2015). Ethnic differences in risk factors for obesity in New Zealand infants J Epidemiol Community Health, 69(6), 516-22 | Intervention/exposure, Outcome
1096 | Howie, P. W.,Forsyth, J. S.,Ogston, S. A.,Clark, A.,Du Florey, V. C. (1990). Protective effect of breat feeding against infection British Medical Journal, 300(6716), 11-16 | Outcome
1097 | Howie, P. W.,Forsyth, J. S.,Ogston, S. A.,Clark, A.,Florey, C. (1990). Protective effect of breastfeeding against infection… this article originally appeared in the British Medical Journal, V. 300. Reproduced with permission Breastfeeding Review, 2(1), 7-15 9p | Outcome
1098 | Howie, P. W.,Forsyth, J. S.,Ogston, S. A.,Clark, A.,Florey, C. D. (1990). Protective effect of breast feeding against infection BMJ, 300(6716), 11-6 | Outcome
1099 | Hoyle, B.,Yunus, M.,Chen, L. C. (1980). Breast-feeding and food intake among children with acute diarrheal disease The American journal of clinical nutrition, 33(11), 2365-2371 | Country, Study design
1100 | Hromadova, M.,Kostalova, L.,Leskova, L.,Kapellerova, A. (1997). Relationship between the duration of the breast-feeding period and the lipoprotein profile of children at the age of 13 years Physiol Res, 46(1), 21-5 | Size of study groups
1101 | Huang, D. Y.,Lanza, H. I.,Anglin, M. D. (2014). Trajectory of Adolescent Obesity: Exploring the Impact of Prenatal to Childhood Experiences J Child Fam Stud, 23(6), 1090-1101 | Outcome
1102 | Huang, J.,Peters, K. E.,Vaughn, M. G.,Witko, C. (2014). Breastfeeding and trajectories of children’s cognitive development Dev Sci, 17(3), 452-61 | Outcome
1103 | Huang, J.,Vaughn, M. G.,Kremer, K. P. (2015). Breastfeeding and child development outcomes: an investigation of the nurturing hypothesis Matern Child Nutr, #volume#(#issue#), #Pages# | Outcome
1104 | Huang, R. C.,Burke, V.,Newnham, J. P.,Stanley, F. J.,Kendall, G. E.,Landau, L. I.,Oddy, W. H.,Blake, K. V.,Palmer, L. J.,Beilin, L. J. (2007). Perinatal and childhood origins of cardiovascular disease Int J Obes (Lond), 31(2), 236-44 | Outcome
1105 | Huang, R. C.,Mori, T. A.,Beilin, L. J. (2012). Early life programming of cardiometabolic disease in the Western Australian pregnancy cohort (Raine) study Clinical and Experimental Pharmacology and Physiology, 39(11), 973-978 | Study design
1106 | Huffman, S. L.,Dewey, K. G.,Schofield, D. (2010). Moving ahead with maternal, infant, and young child nutrition: need to integrate actions Food Nutr Bull, 31(2 Suppl), S99 | Study design
1107 | Huffman, S. L.,Lopez de Romana, G.,Madrid, S.,Brown, K. H.,Bentley, M.,Black, R. E. (1991). Do child feeding practices change due to diarrhoea in the Central Peruvian Highlands? J Diarrhoeal Dis Res, 9(4), 295-300 | Study design, Outcome
1108 | Huh, S. Y.,Rifas-Shiman, S. L.,Taveras, E. M.,Oken, E.,Gillman, M. W. (2011). Timing of solid food introduction and risk of obesity in preschool-aged children Pediatrics, 127(3), e544-51 | Intervention/exposure
1109 | Hummel, M.,Fuchtenbusch, M.,Schenker, M.,Ziegler, A. G. (2000). No major association of breast-feeding, vaccinations, and childhood viral diseases with early islet autoimmunity in the German BABYDIAB Study Diabetes Care, 23(7), 969-74 | Outcome
1110 | Hummel, S.,Pfluger, M.,Kreichauf, S.,Hummel, M.,Ziegler, A. G. (2009). Predictors of overweight during childhood in offspring of parents with type 1 diabetes Diabetes Care, 32(5), 921-5 | Outcome
1111 | Hundt, G. A.,Forman, M. R. (1993). Interfacing anthropology and epidemiology: the Bedouin Arab Infant Feeding Study Soc Sci Med, 36(7), 957-64 | Study design, Outcome
1112 | Hure, A. J.,Collins, C. E.,Smith, R. (2012). A longitudinal study of maternal folate and vitamin B12 status in pregnancy and postpartum, with the same infant markers at 6 months of age Matern Child Health J, 16(4), 792-801 | Size of study groups
1113 | Hurtado, J. A.,Iznaola, C.,Pena, M.,Ruiz, J.,Pena-Quintana, L.,Kajarabille, N.,Rodriguez-Santana, Y.,Sanjurjo, P.,Aldamiz-Echevarria, L.,Ochoa, J.,Lara-Villoslada, F. (2015). Effects of Maternal Omega-3 Supplementation on Fatty Acids and on Visual and Cognitive Development J Pediatr Gastroenterol Nutr, 61(4), 472-80 | Intervention/exposure
1114 | Husk, J. S.,Keim, S. A. (2015). Breastfeeding and Autism Spectrum Disorder in the National Survey of Children’s Health Epidemiology, 26(4), 451-457 | Study design
1115 | Hutchison, B. L.,Thompson, J. M.,Mitchell, E. A. (2015). Infant care practices related to sudden unexpected death in infancy: a 2013 survey N Z Med J, 128(1408), 15-22 | Study design, Outcome
1116 | Huttunen, J. K.,Saarinen, U. M.,Kostiainen, E.,Siimes, M. A. (1983). Fat composition of the infant diet does not influence subsequent serum lipid levels in man Atherosclerosis, 46(1), 87-94 | Intervention/exposure
1117 | Huurre, A.,Laitinen, K.,Rautava, S.,Korkeamaki, M.,Isolauri, E. (2008). Impact of maternal atopy and probiotic supplementation during pregnancy on infant sensitization: a double-blind placebo-controlled study Clin Exp Allergy, 38(8), 1342-8 | Outcome
1118 | Huus, K.,Ludvigsson, J. F.,Enskar, K.,Ludvigsson, J. (2008). Exclusive breastfeeding of Swedish children and its possible influence on the development of obesity: a prospective cohort study BMC Pediatr, 8(#issue#), 42 | Outcome
1119 | Huybrechts, I.,De Vriendt, T.,Breidenassel, C.,Rogiers, J.,Vanaelst, B.,Cuenca-Garcia, M.,Moreno, L. A.,Gonzalez-Gross, M.,Roccaldo, R.,Kafatos, A.,Clays, E.,Bueno, G.,Beghin, L.,Sjostrom, M.,Manios, Y.,Molnar, D.,Pisa, P. T.,De Henauw, S. (2014). Mechanisms of stress, energy homeostasis and insulin resistance in European adolescents--the HELENA study Nutr Metab Cardiovasc Dis, 24(10), 1082-9 | Study design
1120 | Hwang, J. B.,Lee, S. H.,Kang, Y. N.,Kim, S. P.,Suh, S. I.,Kam, S. (2007). Indexes of suspicion of typical cow’s milk protein-induced enterocolitis J Korean Med Sci, 22(6), 993-7 | Participant health, Intervention/exposure
1121 | Hyland, F. (1988). Breastfeeding: for those who won’t Community Outlook, #volume#(#issue#), 11-2 | Study design
1122 | Hysing, M.,Harvey, A. G.,Torgersen, L.,Ystrom, E.,Reichborn-Kjennerud, T.,Sivertsen, B. (2014). Trajectories and predictors of nocturnal awakenings and sleep duration in infants J Dev Behav Pediatr, 35(5), 309-16 | Outcome
1123 | Iacono, G.,Merolla, R.,D’Amico, D.,Bonci, E.,Cavataio, F.,Di Prima, L.,Scalici, C.,Indinnimeo, L.,Averna, M. R.,Carroccio, A. (2005). Gastrointestinal symptoms in infancy: a population-based prospective study Dig Liver Dis, 37(6), 432-8 | Intervention/exposure, Outcome
1124 | Iannotti, L. L.,Zavaleta, N.,León, Z.,Caulfield, E. L. (2009). Growth and body composition of Peruvian infants in a peri urban setting Food and Nutrition Bulletin, 30(3), 245-253 | Intervention/exposure
1125 | Imai, C. M.,Gunnarsdottir, I.,Thorisdottir, B.,Halldorsson, T. I.,Thorsdottir, I. (2014). Associations between infant feeding practice prior to six months and body mass index at six years of age Nutrients, 6(4), 1608-17 | Intervention/exposure, Size of study groups
1126 | Inamo, Y.,Hasegawa, M.,Saito, K.,Hayashi, R.,Ishikawa, T.,Yoshino, Y.,Hashimoto, K.,Fuchigami, T. (2011). Serum vitamin D concentrations and associated severity of acute lower respiratory tract infections in Japanese hospitalized children Pediatr Int, 53(2), 199-201 | Study design, Size of study groups
1127 | Inanç, B. B.,Şahin, D. S.,Oǧuzüncül, A. F.,Bindak, R.,Mungan, F. (2012). Prevalence of obesity in elementary schools in mardin, south-eastern of turkey: A preliminary study Balkan Medical Journal, 29(4), 424-430 | Study design
1128 | Infante-Rivard, C. (1993). Childhood asthma and indoor environmental risk factors Am J Epidemiol, 137(8), 834-44 | Outcome
1129 | Infante-Rivard, C.,Amre, D.,Gautrin, D.,Malo, J. L. (2001). Family size, day-care attendance, and breastfeeding in relation to the incidence of childhood asthma Am J Epidemiol, 153(7), 653-8 | Outcome
1130 | Infante-Rivard, C.,Fortier, I.,Olson, E. (2000). Markers of infection, breast-feeding and childhood acute lymphoblastic leukaemia Br J Cancer, 83(11), 1559-64 | Outcome
1131 | Innis, S. M. (1992). Human milk and formula fatty acids J Pediatr, 120(4 Pt 2), S56-61 | Study design
1132 | Innis, S. M.,Auestad, N.,Siegman, J. S. (1996). Blood lipid docosahexaenoic and arachidonic acid in term gestation infants fed formulas with high docosahexaenoic acid, low eicosapentaenoic acid fish oil Lipids, 31(6), 617-25 | Size of study groups
1133 | Innis, S. M.,Diersen-Schade, D. A.,Akrabawi, S. S. (1995). Prospective evaluation of preferential looking acuity in healthy term infants fed infant formula or breast fed Pediatric research, 37(4), 308a | Publication status
1134 | Innis, S. M.,Friesen, R. W. (2007). Maternal DHA supplementation in pregnancy: a double blind randomized prospective trial of maternal N-3 fatty acid status, human milk fatty acids and infant development Pediatric Academic Societies Annual Meeting; 2007 May 5-8; Toronto, Canada, #volume#(#issue#), #Pages# | Publication status
1135 | Innis, S. M.,Nelson, C. M.,Lwanga, D.,Rioux, F. M.,Waslen, P. (1996). Feeding formula without arachidonic acid and docosahexaenoic acid has no effect on preferential looking acuity or recognition memory in healthy full-term infants at 9 mo of age Am J Clin Nutr, 64(1), 40-6 | Study design, Intervention/exposure
1136 | Innis, S. M.,Nelson, C. M.,Rioux, M. F.,King, D. J. (1994). Development of visual acuity in relation to plasma and erythrocyte omega-6 and omega-3 fatty acids in healthy term gestation infants Am J Clin Nutr, 60(3), 347-52 | Intervention/exposure
1137 | Inostroza, J.,Haschke, F.,Steenhout, P.,Grathwohl, D.,Nelson, S. E.,Ziegler, E. E. (2014). Low-protein formula slows weight gain in infants of overweight mothers J Pediatr Gastroenterol Nutr, 59(1), 70-7 | Intervention/exposure
1138 | Iron-Segev, S.,Peterson, K. E.,Gillman, M. W.,Williams, C. M.,Austin, S. B.,Field, A. E. (2013). Associations of breastfeeding with bulimic behaviors and eating disorders among adolescents Int J Eat Disord, 46(8), 834-40 | Outcome
1139 | Isaacs, C. E.,Jia, J. H. (2004). The anti-infective activity of human milk is potentially greater than the sum of its microbicidal components Adv Exp Med Biol, 554(#issue#), 439-41 | Study design, Outcome
1140 | Isaacs, E. B.,Fischl, B. R.,Quinn, B. T.,Chong, W. K.,Gadian, D. G.,Lucas, A. (2010). Impact of breast milk on intelligence quotient, brain size, and white matter development Pediatr Res, 67(4), 357-62 | Participant health
1141 | Islam, M. A.,Rahman, M. M.,Mahalanabis, D. (1994). Maternal and socioeconomic factors and the risk of severe malnutrition in a child: a case-control study Eur J Clin Nutr, 48(6), 416-24 | Country
1142 | Islam, M. A.,Rahman, M. M.,Mahalanabis, D.,Rahman, A. K. (1996). Death in a diarrhoeal cohort of infants and young children soon after discharge from hospital: risk factors and causes by verbal autopsy J Trop Pediatr, 42(6), 342-7 | Country
1143 | Isolauri, E. (2005). Nutrition, allergy, mucosal immunology and intestinal microbiota: the effects of maternal nutrition during pregnancy and breast feeding on the risk of allergic disease ClinicalTrials.gov [http://clinicaltrials.gov], #volume#(#issue#), #Pages# | Publication status
1144 | Ito, J.,Fujiwara, T. (2014). Breastfeeding and risk of atopic dermatitis up to the age 42 months: a birth cohort study in Japan Ann Epidemiol, 24(4), 267-72 | Intervention/exposure
1145 | Ivakhnenko, O. S.,Nyankovskyy, S. L. (2013). Effect of the specific infant formula mixture of oligosaccharides on local immunity and development of allergic and infectious disease in young children: Randomized study Pediatria Polska, 88(5), 398-404 | Outcome
1146 | Ivanovic, D.,Ivanovic, R.,Buitron, C. (1987). Nutritional status, birth weight and breast feeding of elementary first grade Chilean students Nutrition Reports International, 36(6), 1347-1361 | Study design
1147 | Ivarsson, A.,Hernell, O.,Stenlund, H.,Persson, L. A. (2002). Breast-feeding protects against celiac disease Am J Clin Nutr, 75(5), 914-21 | Outcome
1148 | Ivarsson, A.,Persson, L. A.,Nystrom, L.,Ascher, H.,Cavell, B.,Danielsson, L.,Dannaeus, A.,Lindberg, T.,Lindquist, B.,Stenhammar, L.,Hernell, O. (2000). Epidemic of coeliac disease in Swedish children Acta Paediatr, 89(2), 165-71 | Study design, Intervention/exposure
1149 | Izadi, V.,Kelishadi, R.,Qorbani, M.,Esmaeilmotlagh, M.,Taslimi, M.,Heshmat, R.,Ardalan, G.,Azadbakht, L. (2013). Duration of breast-feeding and cardiovascular risk factors among Iranian children and adolescents: the CASPIAN III study Nutrition, 29(5), 744-51 | Study design
1150 | J. M, Hamid Jan,Mitra, Amal K.,H, Hasmiza,C. D, Pim,L. O, Ng,W. M, Wan Manan (2011). Effect of Gender and Nutritional Status on Academic Achievement and Cognitive Function among Primary School Children in a Rural District in Malaysia Malaysian Journal of Nutrition, 17(2), 189-200 12p | Study design
1151 | Jackson, D. B.,Beaver, K. M. (2015). The Association Between Breastfeeding Exposure and Duration, Neuropsychological Deficits, and Psychopathic Personality Traits in Offspring: The Moderating Role of 5HTTLPR Psychiatr Q, #volume#(#issue#), #Pages# | Outcome
1152 | Jackson, J. M.,Mourino, A. P. (1999). Pacifier use and otitis media in infants twelve months of age or younger Pediatr Dent, 21(4), 255-60 | Study design
1153 | Jacobson, J. L.,Jacobson, S. W. (2002). Association of prenatal exposure to an environmental contaminant with intellectual function in childhood J Toxicol Clin Toxicol, 40(4), 467-75 | Size of study groups
1154 | Jacobson, J. L.,Jacobson, S. W.,Muckle, G.,Kaplan-Estrin, M.,Ayotte, P.,Dewailly, E. (2008). Beneficial effects of a polyunsaturated fatty acid on infant development: evidence from the inuit of arctic Quebec J Pediatr, 152(3), 356-64 | Intervention/exposure
1155 | Jacobson, S. W.,Chiodo, L. M.,Jacobson, J. L. (1999). Breastfeeding effects on intelligence quotient in 4- and 11-year-old children Pediatrics, 103(5), e71 | Outcome
1156 | Jacoby, P.,Carville, K. S.,Hall, G.,Riley, T. V.,Bowman, J.,Leach, A. J.,Lehmann, D. (2011). Crowding and other strong predictors of upper respiratory tract carriage of otitis media-related bacteria in Australian Aboriginal and non-Aboriginal children Pediatr Infect Dis J, 30(6), 480-5 | Outcome
1157 | Jaganath, D.,Saito, M.,Gilman, R. H.,Queiroz, D. M.,Rocha, G. A.,Cama, V.,Cabrera, L.,Kelleher, D.,Windle, H. J.,Crabtree, J. E.,Checkley, W. (2014). First detected Helicobacter pylori infection in infancy modifies the association between diarrheal disease and childhood growth in Peru Helicobacter, 19(4), 272-9 | Intervention/exposure, Outcome
1158 | Jain, L. (2014). Our babies are what we feed them Clin Perinatol, 41(2), xv-xvii | Study design
1159 | Jain, M. K.,Vora, J. N.,Kale, V. V.,Iyyer, L.,Irani, S. F. (1984). A study of non-epidemic diarrhea in the newborns Indian Pediatr, 21(1), 56-60 | Country
1160 | Jain, R.,Acharya, A. S. (2010). Supplemental folic acid in pregnancy and childhood asthma Natl Med J India, 23(6), 351-2 | Study design
1161 | Jakobsen, C.,Paerregaard, A.,Munkholm, P.,Wewer, V. (2013). Environmental factors and risk of developing paediatric inflammatory bowel disease -- a population based study 2007-2009 J Crohns Colitis, 7(1), 79-88 | Outcome
1162 | Jalevik, B.,Noren, J. G.,Klingberg, G.,Barregard, L. (2001). Etiologic factors influencing the prevalence of demarcated opacities in permanent first molars in a group of Swedish children Eur J Oral Sci, 109(4), 230-4 | Study design
1163 | James, J.,Evans, J.,Male, P.,Pallister, C.,Hendrikz, J. K.,Oakhill, A. (1988). Iron deficiency in inner city pre-school children: development of a general practice screening programme J R Coll Gen Pract, 38(311), 250-2 | Study design
1164 | James, M. (1986). Child’s nutritional needs: nature’s wonderful formula Nurs J India, 77(7), 180-1, 196 | Study design
1165 | Jamieson EC,Abbasi KA,Cockburn F,Farquharson J,Logan RW,Patrick WA (1994). Effect of diet on term infant cerebral cortex fatty acid composition World Rev Nutr Diet, 75(#issue#), 139-41 | Participant health, Size of study groups
1166 | Janevic, T.,Petrovic, O.,Bjelic, I.,Kubera, A. (2010). Risk factors for childhood malnutrition in Roma settlements in Serbia BMC Public Health, 10(#issue#), 509 | Study design
1167 | Janowitz, B.,Nichols, D. J. (1983). Child survivorship and pregnancy spacing in Iran J Biosoc Sci, 15(1), 35-46 | Outcome
1168 | Jansen, A. A. (1982). Malnutrition and child feeding practices in the Kingdom of Tonga J Trop Pediatr, 28(4), 202-8 | Study design
1169 | Jansen, H.,Huiting, H. G.,Scholtens, S.,Sauer, P. J.,Stolk, R. P. (2011). HbA1c in nondiabetic Dutch infants aged 8-12 months: the GECKO-Drenthe birth cohort study Diabetes Care, 34(2), 403-5 | Study design
1170 | Jansen, M. A.,Tromp,, II,Kiefte-de Jong, J. C.,Jaddoe, V. W.,Hofman, A.,Escher, J. C.,Hooijkaas, H.,Moll, H. A. (2014). Infant feeding and anti-tissue transglutaminase antibody concentrations in the Generation R Study Am J Clin Nutr, 100(4), 1095-101 | Outcome
1171 | Jarvisalo, M. J.,Hutri-Kahonen, N.,Juonala, M.,Mikkila, V.,Rasanen, L.,Lehtimaki, T.,Viikari, J.,Raitakari, O. T. (2009). Breast feeding in infancy and arterial endothelial function later in life. The Cardiovascular Risk in Young Finns Study Eur J Clin Nutr, 63(5), 640-5 | Intervention/exposure
1172 | Javed, A.,Yoo, K. H.,Agarwal, K.,Jacobson, R. M.,Li, X.,Juhn, Y. J. (2013). Characteristics of children with asthma who achieved remission of asthma J Asthma, 50(5), 472-9 | Participant health
1173 | Jazar, A. S.,Takruri, H. R.,Khuri-Bulos, N. A. (2011). Vitamin D status in a sample of preschool children aged from 1 to 6 years visiting the pediatrics clinic at Jordan University Hospital Jordan Medical Journal, 45(4), 308-316 | Study design
1174 | Jedrychowski, W.,Maugeri, U.,Perera, F.,Stigter, L.,Jankowski, J.,Butscher, M.,Mroz, E.,Flak, E.,Skarupa, A.,Sowa, A. (2011). Cognitive function of 6-year old children exposed to mold-contaminated homes in early postnatal period. Prospective birth cohort study in Poland Physiol Behav, 104(5), 989-95 | Intervention/exposure
1175 | Jedrychowski, W.,Perera, F.,Jankowski, J.,Butscher, M.,Mroz, E.,Flak, E.,Kaim, I.,Lisowska-Miszczyk, I.,Skarupa, A.,Sowa, A. (2012). Effect of exclusive breastfeeding on the development of children’s cognitive function in the Krakow prospective birth cohort study Eur J Pediatr, 171(1), 151-8 | Intervention/exposure
1176 | Jeffery, A. N.,Metcalf, B. S.,Hosking, J.,Murphy, M. J.,Voss, L. D.,Wilkin, T. J. (2006). Little evidence for early programming of weight and insulin resistance for contemporary children: EarlyBird Diabetes Study report 19 Pediatrics, 118(3), 1118-23 | Outcome
1177 | Jelding-Dannemand, E.,Malby Schoos, A. M.,Bisgaard, H. (2015). Breast-feeding does not protect against allergic sensitization in early childhood and allergy-associated disease at age 7 years J Allergy Clin Immunol, 136(5), 1302-1308 e13 | Intervention/exposure
1178 | Jelliffe DB (1986). Recent developments in breastfeeding Med J Malaysia, 41(#issue#), 59-63 | Study design
1179 | Jelliffee, E. F. (1986). Breastfeeding and the prevention of malnutrition Med J Malaysia, 41(1), 88-92 | Study design
1180 | Jenkins, A. L.,Gyorkos, T. W.,Joseph, L.,Culman, K. N.,Ward, B. J.,Pekeles, G. S.,Mills, E. L. (2004). Risk factors for hospitalization and infection in Canadian Inuit infants over the first year of life--a pilot study Int J Circumpolar Health, 63(1), 61-70 | Size of study groups
1181 | Jenkins, J. M.,Foster, E. M. (2014). The effects of breastfeeding exclusivity on early childhood outcomes Am J Public Health, 104 Suppl 1(#issue#), S128-35 | Outcome
1182 | Jensen, B. H.,Röser, D.,Andreassen, B. U.,Olsen, K. E. P.,Nielsen, H. V.,Roldgaard, B. B.,Schjørring, S.,Mirsepasi-Lauridsen, H. C.,Jørgensen, S. L.,Mortensen, E. M.,Petersen, A. M.,Krogfelt, K. A. (2015). Childhood diarrhoea in Danish day care centres could be associated with infant colic, low birthweight and antibiotics Acta Paediatrica, International Journal of Paediatrics, #volume#(#issue#), #Pages# | Size of study groups, Intervention/exposure
1183 | Jensen, C. L.,Chen, H.,Fraley, J. K.,Anderson, R. E.,Heird, W. C. (1996). Biochemical effects of dietary linoleic/alpha-linolenic acid ratio in term infants Lipids, 31(1), 107-13 | Intervention/exposure
1184 | Jensen, C. L.,Prager, T. C.,Fraley, J. K.,Chen, H.,Anderson, R. E.,Heird, W. C. (1997). Effect of dietary linoleic/alpha-linolenic acid ratio on growth and visual function of term infants J Pediatr, 131(2), 200-9 | Intervention/exposure
1185 | Jensen, C. L.,Prager, T. C.,Zou, Y.,Fraley, J. K.,Maude, M.,Anderson, R. E.,Heird, W. C. (1999). Effects of maternal docosahexaenoic acid supplementation on visual function and growth of breast-fed term infants Lipids, 34 Suppl(#issue#), S225 | Publication status
1186 | Jensen, E. T.,Kappelman, M. D.,Kim, H. P.,Ringel-Kulka, T.,Dellon, E. S. (2013). Early life exposures as risk factors for pediatric eosinophilic esophagitis J Pediatr Gastroenterol Nutr, 57(1), 67-71 | Size of study groups, Outcome
1187 | Jensen, S. M.,Ritz, C.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F. (2015). Infant BMI peak, breastfeeding, and body composition at age 3 y Am J Clin Nutr, 101(2), 319-25 | Outcome
1188 | Jensen, T. K.,Grandjean, P.,Jorgensen, E. B.,White, R. F.,Debes, F.,Weihe, P. (2005). Effects of breast feeding on neuropsychological development in a community with methylmercury exposure from seafood J Expo Anal Environ Epidemiol, 15(5), 423-30 | Outcome
1189 | Jeris, L. S.,Thies, P. A. (1980). Infant feeding practices and dental health. Part 1: the biological specificity of human milk Bull Mich Dent Hyg Assoc, 10(3), 9-10 | Study design
1190 | Jiang, M.,Foster, E. M. (2013). Duration of breastfeeding and childhood obesity: a generalized propensity score approach Health Serv Res, 48(2 Pt 1), 628-51 | Outcome
1191 | Jiang, M.,Foster, E. M.,Gibson-Davis, C. M. (2011). Breastfeeding and the child cognitive outcomes: a propensity score matching approach Matern Child Health J, 15(8), 1296-307 | Outcome
1192 | Jin, C.,MacKay Rossignol, A. (1993). Effects of passive smoking on respiratory illness from birth to age eighteen months, in Shanghai, People’s Republic of China Journal of Pediatrics, 123(4), 553-558 | Study design, Intervention/exposure
1193 | Jin, H. J.,Lee, J. H.,Kim, M. K. (2013). The prevalence of vitamin D deficiency in iron-deficient and normal children under the age of 24 months Blood Research, 48(1), 40-45 | Study design
1194 | Jing, H.,Gilchrist, J. M.,Badger, T. M.,Pivik, R. T. (2010). A longitudinal study of differences in electroencephalographic activity among breastfed, milk formula-fed, and soy formula-fed infants during the first year of life Early Hum Dev, 86(2), 119-25 | Outcome
1195 | Jing, H.,Pivik, R. T.,Dykman, R. A.,Gilchrist, J. M.,Badger, T. M. (2007). Effects of breast milk and milk formula diets on synthesized speech sound-induced event-related potentials in 3- and 6-month-old infants Dev Neuropsychol, 31(3), 349-62 | Size of study groups
1196 | Jing, H.,Xu, H.,Wan, J.,Yang, Y.,Ding, H.,Chen, M.,Li, L.,Lv, P.,Hu, J.,Yang, J. (2014). Effect of breastfeeding on childhood BMI and obesity: the China Family Panel Studies Medicine (Baltimore), 93(10), e55 | Study design
1197 | Johansson, C.,Samuelsson, U.,Ludvigsson, J. (1994). A high weight gain early in life is associated with an increased risk of type 1 (insulin-dependent) diabetes mellitus Diabetologia, 37(1), 91-4 | Outcome
1198 | Johnsen, D. C. (1982). Characteristics and backgrounds of children with “nursing caries” Pediatr Dent, 4(3), 218-24 | Study design, Intervention/exposure
1199 | Johnsen, D. C.,Gerstenmaier, J. H.,DiSantis, T. A.,Berkowitz, R. J. (1986). Susceptibility of nursing-caries children to future approximal molar decay Pediatr Dent, 8(3), 168-70 | Study design
1200 | Johnsen, D. C.,Gerstenmaier, J. H.,Schwartz, E.,Michal, B. C.,Parrish, S. (1984). Background comparisons of pre-31/2-year-old children with nursing caries in four practice settings Pediatr Dent, 6(1), 50-4 | Study design
1201 | Johnson, C. A.,Lieberman, B.,Hassanein, R. E. (1985). The relationship of breast feeding to third-day bilirubin levels J Fam Pract, 20(2), 147-52 | Study design, Intervention/exposure
1202 | Johnson, C. C.,Ownby, D. R.,Alford, S. H.,Havstad, S. L.,Williams, L. K.,Zoratti, E. M.,Peterson, E. L.,Joseph, C. L. (2005). Antibiotic exposure in early infancy and risk for childhood atopy J Allergy Clin Immunol, 115(6), 1218-24 | Outcome
1203 | Johnson, D. L.,Swank, P. R.,Howie, V. M.,Baldwin, C. D.,Owen, M. (1996). Breast feeding and children’s intelligence Psychol Rep, 79(3 Pt 2), 1179-85 | Outcome
1204 | Johnson, L.,van Jaarsveld, C. H.,Llewellyn, C. H.,Cole, T. J.,Wardle, J. (2014). Associations between infant feeding and the size, tempo and velocity of infant weight gain: SITAR analysis of the Gemini twin birth cohort Int J Obes (Lond), 38(7), 980-7 | Outcome
1205 | Johnston, B. D.,Huebner, C. E.,Anderson, M. L.,Tyll, L. T.,Thompson, R. S. (2006). Healthy steps in an integrated delivery system: child and parent outcomes at 30 months Arch Pediatr Adolesc Med, 160(8), 793-800 | Outcome
1206 | Johnston, P. K. (1984). Getting enough to grow on Am J Nurs, 84(3), 336-9 | Study design, Intervention/exposure, Outcome
1207 | Jonas, W.,Atkinson, L.,Steiner, M.,Meaney, M. J.,Wazana, A.,Fleming, A. S. (2015). Breastfeeding and maternal sensitivity predict early infant temperament Acta Paediatr, 104(7), 678-86 | Outcome
1208 | Jones EG,Matheny RJ (1993). Relationship between infant feeding and exclusion rate from child care because of illness J Am Diet Assoc, 93(#issue#), 809-11 | Study design, Outcome
1209 | Jones, A. (2015). INTERGENERATIONAL EDUCATIONAL ATTAINMENT, FAMILY CHARACTERISTICS AND CHILD OBESITY J Biosoc Sci, #volume#(#issue#), 1-20 | Study design
1210 | Jones, D. (1987). Infant feeding. Breast-feeding practices Nurs Times, 83(3), 56-7 | Outcome
1211 | Jones, F.,Green, M. (1996). The B.C. Baby-Friendly Initiative Nurs BC, 28(5), 7-8 | Study design
1212 | Jones, G.,Hynes, K. L.,Dwyer, T. (2013). The association between breastfeeding, maternal smoking in utero, and birth weight with bone mass and fractures in adolescents: a 16-year longitudinal study Osteoporos Int, 24(5), 1605-11 | Outcome
1213 | Jones, G.,Riley, M.,Dwyer, T. (2000). Breastfeeding in early life and bone mass in prepubertal children: a longitudinal study Osteoporos Int, 11(2), 146-52 | Outcome
1214 | Jones, I. E.,Williams, S. M.,Goulding, A. (2004). Associations of birth weight and length, childhood size, and smoking with bone fractures during growth: evidence from a birth cohort study Am J Epidemiol, 159(4), 343-50 | Outcome
1215 | Jones, M. E.,Swerdlow, A. J.,Gill, L. E.,Goldacre, M. J. (1998). Pre-natal and early life risk factors for childhood onset diabetes mellitus: a record linkage study Int J Epidemiol, 27(3), 444-9 | Intervention/exposure
1216 | Jones, N. A.,McFall, B. A.,Diego, M. A. (2004). Patterns of brain electrical activity in infants of depressed mothers who breastfeed and bottle feed: the mediating role of infant temperament Biol Psychol, 67(1-2), 103-24 | Size of study groups
1217 | Jones, S. M.,Steele, R. W. (2012). Recurrent group B streptococcal bacteremia Clin Pediatr (Phila), 51(9), 884-7 | Study design
1218 | Jones, T. F.,Ingram, L. A.,Fullerton, K. E.,Marcus, R.,Anderson, B. J.,McCarthy, P. V.,Vugia, D.,Shiferaw, B.,Haubert, N.,Wedel, S.,Angulo, F. J. (2006). A case-control study of the epidemiology of sporadic Salmonella infection in infants Pediatrics, 118(6), 2380-7 | Intervention/exposure
1219 | Jonsdottir, O. H.,Kleinman, R. E.,Wells, J. C.,Fewtrell, M. S.,Hibberd, P. L.,Gunnlaugsson, G.,Thorsdottir, I. (2014). Exclusive breastfeeding for 4 versus 6 months and growth in early childhood Acta Paediatr, 103(1), 105-11 | Intervention/exposure
1220 | Jonsdottir, O. H.,Thorsdottir, I.,Gunnlaugsson, G.,Fewtrell, M. S.,Hibberd, P. L.,Kleinman, R. E. (2013). Exclusive breastfeeding and developmental and behavioral status in early childhood Nutrients, 5(11), 4414-28 | Intervention/exposure
1221 | Jonsdottir, O. H.,Thorsdottir, I.,Hibberd, P. L.,Fewtrell, M. S.,Wells, J. C.,Palsson, G. I.,Lucas, A.,Gunnlaugsson, G.,Kleinman, R. E. (2012). Timing of the introduction of complementary foods in infancy: a randomized controlled trial Pediatrics, 130(6), 1038-45 | Intervention/exposure
1222 | Jonville-Béra, A. P.,Autret-Leca, E.,Barbeillon, F.,Paris-Llado, J. (2001). Sudden unexpected death in infants under 3 months of age and vaccination status - A case-control study British Journal of Clinical Pharmacology, 51(3), 271-276 | Outcome
1223 | Jonville-Bera, A. P.,Autret-Leca, E.,Barbeillon, F.,Paris-Llado, J. (2001). Sudden unexpected death in infants under 3 months of age and vaccination status- -a case-control study Br J Clin Pharmacol, 51(3), 271-6 | Outcome
1224 | Jooste, P. L.,Rossouw, L. J.,Steenkamp, H. J.,Rossouw, J. E.,Swanepoel, A. S.,Charlton, D. O. (1991). Effect of breast feeding on the plasma cholesterol and growth of infants J Pediatr Gastroenterol Nutr, 13(2), 139-42 | Country
1225 | Jorgensen, M. H.,Hernell, O.,Lund, P.,Holmer, G.,Michaelsen, K. F. (1996). Visual acuity and erythrocyte docosahexaenoic acid status in breast-fed and formula-fed term infants during the first four months of life Lipids, 31(1), 99-105 | Size of study groups
1226 | Jørgensen, M. H.,Hølmer, G.,Lund, P.,Hernell, O.,Michaelsen, K. F. (1998). Effect of formula supplemented with docosahexaenoic acid and γ- linolenic acid on fatty acid status and visual acuity in term infants Journal of Pediatric Gastroenterology and Nutrition, 26(4), 412-421 | Size of study groups
1227 | Jorgensen, M. H.,Nielsen, P. K.,Michaelsen, K. F.,Lund, P.,Lauritzen, L. (2006). The composition of polyunsaturated fatty acids in erythrocytes of lactating mothers and their infants Matern Child Nutr, 2(1), 29-39 | Size of study groups, Intervention/exposure
1228 | Jourdan-Da Silva, N.,Perel, Y.,Mechinaud, F.,Plouvier, E.,Gandemer, V.,Lutz, P.,Vannier, J. P.,Lamagnere, J. L.,Margueritte, G.,Boutard, P.,Robert, A.,Armari, C.,Munzer, M.,Millot, F.,De Lumley, L.,Berthou, C.,Rialland, X.,Pautard, B.,Hemon, D.,Clavel, J. (2004). Infectious diseases in the first year of life, perinatal characteristics and childhood acute leukaemia Br J Cancer, 90(1), 139-45 | Outcome
1229 | Jovanovic, D.,Ilic, N.,Miljkovic-Selimovic, B.,Djokic, D.,Relic, T.,Tambur, Z.,Doder, R.,Kostic, G. (2015). Campylobacter jejuni infection and IgE sensitization in up to 2-year-old infants Vojnosanit Pregl, 72(2), 140-7 | Study design, Size of study groups
1230 | Joventino, Emanuella Silva,Gomes Coutinho, Robson,de Castro Bezerra, Karine,de Almeida, Paulo CÃ©sar,Oliveira Batista OriÃ¡, MÃ´nica,Barbosa Ximenes, Lorena (2013). Self-effectiveness in preventing diarrhea and child care: a transversal study Online Brazilian Journal of Nursing, 12(2), 1-1 1p | Study design
1231 | Juambeltz, J. C.,Kula, K.,Perman, J. (1993). Nursing caries and lactose intolerance ASDC J Dent Child, 60(4), 377-84 | Study design, Intervention/exposure
1232 | Juez, G.,Diaz, S.,Casado, M. E.,Duran, E.,Salvatierra, A. M.,Peralta, O.,Croxatto, H. B. (1983). Growth pattern of selected urban Chilean infants during exclusive breast-feeding Am J Clin Nutr, 38(3), 462-8 | Intervention/exposure
1233 | Juliusson, P. B.,Roelants, M.,Hoppenbrouwers, K.,Hauspie, R.,Bjerknes, R. (2011). Growth of Belgian and Norwegian children compared to the WHO growth standards: prevalence below −2 and above +2 SD and the effect of breastfeeding Arch Dis Child, 96(10), 916-21 | Study design
1234 | Julvez, J.,Guxens, M.,Carsin, A. E.,Forns, J.,Mendez, M.,Turner, M. C.,Sunyer, J. (2014). A cohort study on full breastfeeding and child neuropsychological development: the role of maternal social, psychological, and nutritional factors Dev Med Child Neurol, 56(2), 148-56 | Outcome
1235 | Julvez, J.,Ribas-Fito, N.,Forns, M.,Garcia-Esteban, R.,Torrent, M.,Sunyer, J. (2007). Attention behaviour and hyperactivity at age 4 and duration of breast-feeding Acta Paediatr, 96(6), 842-7 | Outcome
1236 | Jung, E.,Czajka-Narins, D. (1986). Comparison of growth of black and white infants during their first two years of life J Natl Med Assoc, 78(12), 1157-60 | Study design, Intervention/exposure
1237 | Jung, E.,Czajka-Narins, D. M. (1985). Birth weight doubling and tripling times: an updated look at the effects of birth weight, sex, race and type of feeding Am J Clin Nutr, 42(2), 182-9 | Intervention/exposure
1238 | Just, J.,Belfar, S.,Wanin, S.,Pribil, C.,Grimfeld, A.,Duru, G. (2010). Impact of innate and environmental factors on wheezing persistence during childhood J Asthma, 47(4), 412-6 | Participant health
1239 | Juto, P.,Moller, C.,Engberg, S.,Bjorksten, B. (1982). Influence of type of feeding on lymphocyte function and development of infantile allergy Clin Allergy, 12(4), 409-16 | Size of study groups
1240 | Juvonen, P.,Mansson, M.,Andersson, C.,Jakobsson, I. (1996). Allergy development and macromolecular absorption in infants with different feeding regimens during the first three days of life. A three-year prospective follow-up Acta Paediatr, 85(9), 1047-52 | Size of study groups, Intervention/exposure
1241 | Jwa, S. C.,Fujiwara, T.,Kondo, N. (2014). Latent protective effects of breastfeeding on late childhood overweight and obesity: a nationwide prospective study Obesity (Silver Spring), 22(6), 1527-37 | Intervention/exposure
1242 | Kaatsch, P.,Kaletsch, U.,Krummenauer, F.,Meinert, R.,Miesner, A.,Haaf, G.,Michaelis, J. (1996). Case control study on childhood leukemia in Lower Saxony, Germany. Basic considerations, methodology, and summary of results Klin Padiatr, 208(4), 179-85 | Study design, Intervention/exposure
1243 | Kadziela-Olech, H.,Piotrowska-Jastrzebska, J. (2005). The duration of breastfeeding and attention deficit hyperactivity disorder Rocz Akad Med Bialymst, 50(#issue#), 302-6 | Outcome
1244 | Kafouri, S.,Kramer, M.,Leonard, G.,Perron, M.,Pike, B.,Richer, L.,Toro, R.,Veillette, S.,Pausova, Z.,Paus, T. (2013). Breastfeeding and brain structure in adolescence Int J Epidemiol, 42(1), 150-9 | Study design
1245 | Kajantie, E.,Barker, D. J.,Osmond, C.,Forsen, T.,Eriksson, J. G. (2008). Growth before 2 years of age and serum lipids 60 years later: the Helsinki Birth Cohort study Int J Epidemiol, 37(2), 280-9 | Outcome
1246 | Kajosaari, M. (1991). Atopy prophylaxis in high-risk infants. Prospective 5-year follow-up study of children with six months exclusive breastfeeding and solid food elimination Adv Exp Med Biol, 310(#issue#), 453-8 | Publication status
1247 | Kajosaari, M. (1994). Atopy prevention in childhood: the role of diet. Prospective 5-year follow-up of high-risk infants with six months exclusive breastfeeding and solid food elimination Pediatr Allergy Immunol, 5(6 Suppl), 26-8 | Intervention/exposure
1248 | Kajosaari, M.,Saarinen, U. M. (1983). Prophylaxis of atopic disease by six months’ total solid food elimination. Evaluation of 135 exclusively breast-fed infants of atopic families Acta Paediatr Scand, 72(3), 411-4 | Intervention/exposure
1249 | Kale, A.,Deardorff, J.,Lahiff, M.,Laurent, C.,Greenspan, L. C.,Hiatt, R. A.,Windham, G.,Galvez, M. P.,Biro, F. M.,Pinney, S. M.,Teitelbaum, S. L.,Wolff, M. S.,Barlow, J.,Mirabedi, A.,Lasater, M.,Kushi, L. H. (2015). Breastfeeding versus formula-feeding and girls’ pubertal development Matern Child Health J, 19(3), 519-27 | Study design, Outcome
1250 | Kalies, H.,Heinrich, J.,Borte, N.,Schaaf, B.,von Berg, A.,von Kries, R.,Wichmann, H. E.,Bolte, G. (2005). The effect of breastfeeding on weight gain in infants: results of a birth cohort study Eur J Med Res, 10(1), 36-42 | Intervention/exposure
1251 | Kallio, M. J.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J.,Miettinen, T. A. (1992). Exclusive breast-feeding and weaning: effect on serum cholesterol and lipoprotein concentrations in infants during the first year of life Pediatrics, 89(4 Pt 1), 663-6 | Outcome
1252 | Kallio, M. J.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J.,Miettinen, T. A. (1993). Tracking of serum cholesterol and lipoprotein levels from the first year of life Pediatrics, 91(5), 949-54 | Intervention/exposure
1253 | Kalliomaki, M.,Isolauri, E. (2000). Breastfeeding and atopic sensitisation Adv Exp Med Biol, 478(#issue#), 389-90 | Study design
1254 | Kalliomäki, M.,Salminen, S.,Arvilommi, H. (2001). Prenatal and postnatal administration of Lactobacillus GG reduced the occurence of atopic disease in offspring Evidence-Based Medicine, 6(6), 178 | Publication status
1255 | Kamer, B.,Raczynska, J.,Kaczmarek, J.,Lukamowicz, J.,Pasowska, R.,Puchala, B. (1995). Genetic and environmental conditions involved in assessment of the immunological state in children with atopic dermatitis Rocz Akad Med Bialymst, 40(3), 439-47 | Study design, Participant health
1256 | Kanazawa, S. (2015). Breastfeeding is positively associated with child intelligence even net of parental IQ Dev Psychol, 51(12), 1683-9 | Outcome
1257 | Kaplan, B. A.,Mascie-Taylor, C. G. (1985). Biosocial factors in the epidemiology of childhood asthma in a British national sample J Epidemiol Community Health, 39(2), 152-6 | Intervention/exposure
1258 | Karademir, F.,Suleymanoglu, S.,Ersen, A.,Aydinoz, S.,Gultepe, M.,Meral, C.,Ozkaya, H.,Gocmen, I. (2007). Vitamin B12, folate, homocysteine and urinary methylmalonic acid levels in infants Journal of International Medical Research, 35(3), 384-388 | Intervention/exposure
1259 | Karaguzel, G.,Ozer, S.,Akcurin, S.,Turkkahraman, D.,Bircan, I. (2007). Type 1 diabetes-related epidemiological, clinical and laboratory findings. An evaluation with special regard to autoimmunity in children Saudi Med J, 28(4), 584-9 | Participant health
1260 | Karakoç, G. B.,Altintaş, D. U.,Yilmaz, M.,Kendirli, S. G. (2003). Prick Skin Test Results in Children Less Than Three Years-Old Annals of Medical Sciences, 12(3), 85-88 | Participant health
1261 | Karaolis-Danckert, N.,Buyken, A. E.,Kulig, M.,Kroke, A.,Forster, J.,Kamin, W.,Schuster, A.,Hornberg, C.,Keil, T.,Bergmann, R. L.,Wahn, U.,Lau, S. (2008). How pre- and postnatal risk factors modify the effect of rapid weight gain in infancy and early childhood on subsequent fat mass development: results from the Multicenter Allergy Study 90 Am J Clin Nutr, 87(5), 1356-64 | Intervention/exposure
1262 | Karaolis-Danckert, N.,Buyken, A. E.,Sonntag, A.,Kroke, A. (2009). Birth and early life influences on the timing of puberty onset: results from the DONALD (DOrtmund Nutritional and Anthropometric Longitudinally Designed) Study Am J Clin Nutr, 90(6), 1559-65 | Outcome
1263 | Karaolis-Danckert, N.,Gunther, A. L.,Kroke, A.,Hornberg, C.,Buyken, A. E. (2007). How early dietary factors modify the effect of rapid weight gain in infancy on subsequent body-composition development in term children whose birth weight was appropriate for gestational age Am J Clin Nutr, 86(6), 1700-8 | Intervention/exposure
1264 | Karino, S.,Okuda, T.,Uehara, Y.,Toyo-oka, T. (2008). Breastfeeding and prevalence of allergic diseases in Japanese university students Ann Allergy Asthma Immunol, 101(2), 153-9 | Study design
1265 | Karjalainen, S.,Ronning, O.,Lapinleimu, H.,Simell, O. (1999). Association between early weaning, non-nutritive sucking habits and occlusal anomalies in 3-year-old Finnish children Int J Paediatr Dent, 9(3), 169-73 | Outcome
1266 | Kark, J. D.,Troya, G.,Friedlander, Y.,Slater, P. E.,Stein, Y. (1984). Validity of maternal reporting of breast feeding history and the association with blood lipids in 17 year olds in Jerusalem J Epidemiol Community Health, 38(3), 218-25 | Outcome
1267 | Karmaus, W.,Dobai, A. L.,Ogbuanu, I.,Arshard, S. H.,Matthews, S.,Ewart, S. (2008). Long-term effects of breastfeeding, maternal smoking during pregnancy, and recurrent lower respiratory tract infections on asthma in children J Asthma, 45(8), 688-95 | Outcome
1268 | Karunasekera, K. A.,Jayasinghe, J. A.,Alwis, L. W. (2001). Risk factors of childhood asthma: a Sri Lankan study J Trop Pediatr, 47(3), 142-5 | Outcome
1269 | Kaseb, F.,Kimiagar, M.,Ghafarpoor, M.,Valaii, N. (2002). Effect of traditional food supplementation during pregnancy on maternal weight gain and birthweight Int J Vitam Nutr Res, 72(6), 389-93 | Size of study groups
1270 | Kasla, R. R.,Bavdekar, S. B.,Joshi, S. Y.,Hathi, G. S. (1995). Exclusive breastfeeding: protective efficacy Indian J Pediatr, 62(4), 449-53 | Country
1271 | Kass, R. B.,Meumann, F. (1985). Hospitalisation for childhood diarrhoea in Central Australia Aust Clin Rev, 5(19), 178-83 | Study design, Participant health
1272 | Kaste, L. M.,Marianos, D.,Chang, R.,Phipps, K. R. (2010). The assessment of nursing caries and its relationship to high caries in the permanent dentition. 1992 J Indiana Dent Assoc, 89(2), 20-4 | Intervention/exposure
1273 | Katikaneni, R.,Ponnapakkam, T.,Ponnapakkam, A.,Gensure, R. (2009). Breastfeeding does not protect against urinary tract infection in the first 3 months of life, but vitamin D supplementation increases the risk by 76% Clin Pediatr (Phila), 48(7), 750-5 | Outcome
1274 | Kato, T.,Yorifuji, T.,Yamakawa, M.,Inoue, S.,Saito, K.,Doi, H.,Kawachi, I. (2015). Association of breast feeding with early childhood dental caries: Japanese population-based study BMJ Open, 5(3), e006982 | Outcome
1275 | Katoku, Y.,Yamada, M.,Yonekubo, A.,Kuwata, T.,Kobayashi, A.,Sawa, A. (1996). Effect of the cholesterol content of a formula on the lipid compositions of plasma lipoproteins and red blood cell membranes in early infancy Am J Clin Nutr, 64(6), 871-7 | Size of study groups
1276 | Kaufman, H. S.,Frick, O. L. (1981). Prevention of asthma Clin Allergy, 11(6), 549-53 | Intervention/exposure
1277 | Kaur, N.,Deol, R.,Yadav, A. (2014). Correlation of feeding practices and health profile of children Nurs J India, 105(3), 128-30 | Country
1278 | Kawai, T.,Goto, A.,Watanabe, E.,Nagasawa, M.,Yasumura, S. (2011). Lower respiratory tract infections and gastrointestinal infections among mature babies in Japan Pediatr Int, 53(4), 431-45 | Study design
1279 | Kazemi, A.,Tabatabaie, F.,Agha-Ghazvini, M. R.,Kelishadi, R. (2006). The role of rotavirus in acute pediatric diarrhea in Isfahan, Iran Pakistan Journal of Medical Sciences, 22(3), 282-285 | Study design
1280 | Keim, S. A.,Daniels, J. L.,Siega-Riz, A. M.,Herring, A. H.,Dole, N.,Scheidt, P. C. (2012). Breastfeeding and long-chain polyunsaturated fatty acid intake in the first 4 post-natal months and infant cognitive development: an observational study Matern Child Nutr, 8(4), 471-82 | Outcome
1281 | Kellberger, J.,Dressel, H.,Vogelberg, C.,Leupold, W.,Windstetter, D.,Weinmayr, G.,Genuneit, J.,Heumann, C.,Nowak, D.,von Mutius, E.,Radon, K. (2012). Prediction of the incidence and persistence of allergic rhinitis in adolescence: a prospective cohort study J Allergy Clin Immunol, 129(2), 397-402, 402 e1-3 | Intervention/exposure
1282 | Keller, K. M.,Burgin-Wolff, A.,Lippold, R.,Wirth, S.,Lentze, M. J. (1996). The diagnostic significance of IgG cow’s milk protein antibodies re-evaluated Eur J Pediatr, 155(4), 331-7 | Size of study groups, Outcome
1283 | Keller, K. M.,Burgin-Wolff, A.,Menger, H.,Lippold, R.,Wirth, S.,Baumann, W. (1991). IgG, IgA, and IgE antibodies to cow milk proteins in an allergy prevention study Adv Exp Med Biol, 310(#issue#), 467-73 | Intervention/exposure, Outcome
1284 | Kemeny, D. M.,Price, J. F.,Richardson, V.,Richards, D.,Lessof, M. H. (1991). The IgE and IgG subclass antibody response to foods in babies during the first year of life and their relationship to feeding regimen and the development of food allergy J Allergy Clin Immunol, 87(5), 920-9 | Outcome
1285 | Kennedy, K.,Fewtrell, M. S.,Morley, R.,Abbott, R.,Quinlan, P. T.,Wells, J. C.,Bindels, J. G.,Lucas, A. (1999). Double-blind, randomized trial of a synthetic triacylglycerol in formula-fed term infants: effects on stool biochemistry, stool characteristics, and bone mineralization Am J Clin Nutr, 70(5), 920-7 | Outcome
1286 | Kerkhof, M.,Koopman, L. P.,van Strien, R. T.,Wijga, A.,Smit, H. A.,Aalberse, R. C.,Neijens, H. J.,Brunekreef, B.,Postma, D. S.,Gerritsen, J. (2003). Risk factors for atopic dermatitis in infants at high risk of allergy: the PIAMA study Clin Exp Allergy, 33(10), 1336-41 | Outcome
1287 | Kero, P.,Piekkala, P. (1987). Factors affecting the occurrence of acute otitis media during the first year of life Acta Paediatr Scand, 76(4), 618-23 | Outcome
1288 | Kerr, A. A. (1981). Lower respiratory tract illness in Polynesian infants N Z Med J, 93(684), 333-5 | Study design, Outcome
1289 | Keusch, G. T. (1980). Homing in on interventions in the malnutrition-infection complex Am J Clin Nutr, 33(4), 727-9 | Study design
1290 | Kew, S.,Hamilton, J. K.,Ye, C.,Hanley, A. J.,Zinman, B.,Retnakaran, R. (2013). Vitamin D status and cardiometabolic assessment in infancy Pediatr Res, 74(2), 217-22 | Study design, Size of study groups
1291 | Khadivzadeh, T.,Parsai, S. (2004). Effect of exclusive breastfeeding and complementary feeding on infant growth and morbidity East Mediterr Health J, 10(3), 289-94 | Intervention/exposure
1292 | Khalili, H.,Ananthakrishnan, A. N.,Higuchi, L. M.,Richter, J. M.,Fuchs, C. S.,Chan, A. T. (2013). Early life factors and risk of inflammatory bowel disease in adulthood Inflamm Bowel Dis, 19(3), 542-7 | Intervention/exposure
1293 | Khan, F.,Green, F. C.,Forsyth, J. S.,Greene, S. A.,Newton, D. J.,Belch, J. J. (2009). The beneficial effects of breastfeeding on microvascular function in 11- to 14-year-old children Vasc Med, 14(2), 137-42 | Intervention/exposure
1294 | Khanjanasthiti, P.,Nanna, P.,Sawongtrakul, S. (1986). Breast feeding in early neonatal period J Med Assoc Thai, 69 Suppl 2(#issue#), 100-6 | Outcome
1295 | Khanolkar, A. R.,Sovio, U.,Bartlett, J. W.,Wallby, T.,Koupil, I. (2013). Socioeconomic and early-life factors and risk of being overweight or obese in children of Swedish- and foreign-born parents Pediatr Res, 74(3), 356-63 | Intervention/exposure
1296 | Khedr, E. M.,Farghaly, W. M.,Amry Sel, D.,Osman, A. A. (2004). Neural maturation of breastfed and formula-fed infants Acta Paediatr, 93(6), 734-8 | Country, Size of study group
1297 | Kholdi, N.,Zayeri, F.,Bagheban, A. A.,Khodakarim, S.,Ramezankhani, A. (2012). A study of growth failure and its related factors in children from 0 to 2 years in Tehran, Iran Turk J Pediatr, 54(1), 38-44 | Outcome
1298 | Kiechl-Kohlendorfer, U.,Horak, E.,Mueller, W.,Strobl, R.,Haberland, C.,Fink, F. M.,Schwaiger, M.,Gutenberger, K. H.,Reich, H.,Meraner, D.,Kiechl, S. (2007). Neonatal characteristics and risk of atopic asthma in schoolchildren: results from a large prospective birth-cohort study Acta Paediatr, 96(11), 1606-10 | Intervention/exposure
1299 | Kiechl-Kohlendorfer, U.,Peglow, U. P.,Kiechl, S.,Oberaigner, W.,Sperl, W. (2001). Epidemiology of sudden infant death syndrome (SIDS) in the Tyrol before and after an intervention campaign Wien Klin Wochenschr, 113(1-2), 27-32 | Study design, Intervention/exposure
1300 | Kieviet, N.,Hoppenbrouwers, C.,Dolman, K. M.,Berkhof, J.,Wennink, H.,Honig, A. (2015). Risk factors for poor neonatal adaptation after exposure to antidepressants in utero Acta Paediatr, 104(4), 384-91 | Outcome
1301 | Kim, C. S.,Jung, H. W.,Yoo, K. Y. (1993). Prevalence and risk factors of chronic otitis media in Korea: results of a nation-wide survey Acta Otolaryngol, 113(3), 369-75 | Study design
1302 | Kim, H. S.,Kim, Y. H.,Kim, M. J.,Lee, H. S.,Han, Y. K.,Kim, K. W.,Sohn, M. H.,Kim, K. E. (2015). Effect of breastfeeding on lung function in asthmatic children Allergy Asthma Proc, 36(2), 116-22 | Study design, Participant health
1303 | Kim, I.,Pollitt, E. (1987). Differences in the pattern of weight growth of nutritionally at-risk and well-nourished infants Am J Clin Nutr, 46(1), 31-5 | Intervention/exposure
1304 | Kim, M. J.,Na, B.,No, S. J.,Han, H. S.,Jeong, E. H.,Lee, W.,Han, Y.,Hyeun, T. (2010). Nutritional status of vitamin D and the effect of vitamin D supplementation in Korean breast-fed infants J Korean Med Sci, 25(1), 83-9 | Study design, Size of study groups
1305 | Kim, S. K.,Cheong, W. S.,Jun, Y. H.,Choi, J. W.,Son, B. K. (1996). Red blood cell indices and iron status according to feeding practices in infants and young children Acta Paediatr, 85(2), 139-44 | Study design, Participant health
1306 | Kimpimaki, T.,Erkkola, M.,Korhonen, S.,Kupila, A.,Virtanen, S. M.,Ilonen, J.,Simell, O.,Knip, M. (2001). Short-term exclusive breastfeeding predisposes young children with increased genetic risk of Type I diabetes to progressive beta-cell autoimmunity Diabetologia, 44(1), 63-9 | Outcome
1307 | King, D. E. (2002). Statistics. Adult intelligence and breastfeeding International Journal of Childbirth Education, 17(4), 23-23 1p | Publication status
1308 | Kiris, M.,Muderris, T.,Kara, T.,Bercin, S.,Cankaya, H.,Sevil, E. (2012). Prevalence and risk factors of otitis media with effusion in school children in Eastern Anatolia International Journal of Pediatric Otorhinolaryngology, 76(7), 1030-1035 | Study design
1309 | Kitsantas, P.,Gaffney, K. F. (2010). Risk profiles for overweight/obesity among preschoolers Early Hum Dev, 86(9), 563-8 | Outcome
1310 | Kjellman, N. I. (1988). Epidemiology and prevention of allergy Allergy, 43 Suppl 8(#issue#), 39-40 | Study design
1311 | Klag, E. A.,McNamara, K.,Geraghty, S. R.,Keim, S. A. (2015). Associations Between Breast Milk Feeding, Introduction of Solid Foods, and Weight Gain in the First 12 Months of Life Clin Pediatr (Phila), 54(11), 1059-67 | Study design
1312 | Klein, I.,Reif, S.,Farbstein, H.,Halak, A.,Gilat, T. (1998). Preillness non dietary factors and habits in inflammatory bowel disease Ital J Gastroenterol Hepatol, 30(3), 247-51 | Intervention/exposure
1313 | Klein, J. O. (1997). Prevention of recurrent acute otitis media Seminars in Pediatric Infectious Diseases, 8(2), 101-104 | Study design
1314 | Klenovics, K. S.,Boor, P.,Somoza, V.,Celec, P.,Fogliano, V.,Sebekova, K. (2013). Advanced glycation end products in infant formulas do not contribute to insulin resistance associated with their consumption PLoS One, 8(1), e53056 | Study design, Size of study groups
1315 | Klinnert, M. D.,Nelson, H. S.,Price, M. R.,Adinoff, A. D.,Leung, D. Y.,Mrazek, D. A. (2001). Onset and persistence of childhood asthma: predictors from infancy Pediatrics, 108(4), E69 | Outcome
1316 | Klonoff-Cohen, H. S.,Edelstein, S. L.,Lefkowitz, E. S.,Srinivasan, I. P.,Kaegi, D.,Chang, J. C.,Wiley, K. J. (1995). The effect of passive smoking and tobacco exposure through breast milk on sudden infant death syndrome JAMA, 273(10), 795-8 | Outcome
1317 | Knight, S. M.,Toodayan, W.,Caique, W. C.,Kyi, W.,Barnes, A.,Desmarchelier, P. (1992). Risk factors for the transmission of diarrhoea in children: a case-control study in rural Malaysia Int J Epidemiol, 21(4), 812-8 | Participant health
1318 | Knip, M. (2003). Cow’s milk and the new trials for prevention of type 1 diabetes J Endocrinol Invest, 26(3), 265-7 | Study design
1319 | Knishkowy, B.,Palti, H.,Adler, B.,Tepper, D. (1991). Effect of otitis media on development: a community-based study Early Hum Dev, 26(2), 101-11 | Outcome
1320 | Ko, Y.,Kariyawasam, V.,Karnib, M.,Butcher, R.,Samuel, D.,Alrubaie, A.,Rahme, N.,McDonald, C.,Cowlishaw, J.,Katelaris, P.,Barr, G.,Jones, B.,Connor, S.,Paven, G.,Chapman, G.,Park, G.,Gearry, R.,Leong, R. W. (2015). Inflammatory Bowel Disease Environmental Risk Factors: A Population-Based Case-Control Study of Middle Eastern Migration to Australia Clin Gastroenterol Hepatol, 13(8), 1453-63 e1 | Outcome
1321 | Koch, A.,Molbak, K.,Homoe, P.,Sorensen, P.,Hjuler, T.,Olesen, M. E.,Pejl, J.,Pedersen, F. K.,Olsen, O. R.,Melbye, M. (2003). Risk factors for acute respiratory tract infections in young Greenlandic children Am J Epidemiol, 158(4), 374-84 | Outcome
1322 | Kocturk, T. (1988). Infant feeding pattern in three districts of Istanbul J Trop Pediatr, 34(4), 193-7 | Study design, Outcome
1323 | Koehoorn, M.,Karr, C. J.,Demers, P. A.,Lencar, C.,Tamburic, L.,Brauer, M. (2008). Descriptive epidemiological features of bronchiolitis in a population-based cohort Pediatrics, 122(6), 1196-203 | Outcome
1324 | Koenig, H. F. (2014). Breastfeeding education for healthier babies. Baby-Friendly designation improves infant, mother and community health Healthc Exec, 29(4), 46, 48-9 | Study design
1325 | Koh, T. H. (1981). Breast feeding among the Chinese in four countries J Trop Pediatr, 27(2), 88-91 | Study design, Outcome
1326 | Kohler, L.,Meeuwisse, G.,Mortensson, W. (1984). Food intake and growth of infants between six and twenty-six weeks of age on breast milk, cow’s milk formula, or soy formula Acta Paediatr Scand, 73(1), 40-8 | Size of study groups
1327 | Kohn, G.,Sawatzki, G.,van Biervliet, J. P.,Rosseneu, M. (1994). Diet and the essential fatty acid status of term infants Acta Paediatr Suppl, 402(#issue#), 69-74 | Outcome
1328 | Kolacek, S.,Kapetanovic, T.,Luzar, V. (1993). Early determinants of cardiovascular risk factors in adults. B. Blood pressure Acta Paediatr, 82(4), 377-82 | Size of study groups
1329 | Kolacek, S.,Kapetanovic, T.,Zimolo, A.,Luzar, V. (1993). Early determinants of cardiovascular risk factors in adults. A. Plasma lipids Acta Paediatr, 82(8), 699-704 | Size of study groups
1330 | Koletzko S (2015). 2.5 Allergy Prevention through Early Nutrition World Rev Nutr Diet, 113(#issue#), 113-7 | Publication status
1331 | Koletzko, B. (2015). 2.2 Formula feeding World Rev Nutr Diet, 113(#issue#), 97-103 | Study design
1332 | Koletzko, B.,Beyer, J.,Brands, B.,Demmelmair, H.,Grote, V.,Haile, G.,Gruszfeld, D.,Rzehak, P.,Socha, P.,Weber, M. (2013). Early influences of nutrition on postnatal growth Nestle Nutr Inst Workshop Ser, 71(#issue#), 11-27 | Publication status
1333 | Koletzko, B.,Grote, V.,Schiess, S.,Verwied-Jorky, S.,Brands, B.,Demmelmair, H.,Kries, R. (2010). Prevention of pediatric obesity through baby nutrition. [German] Monatsschrift fur Kinderheilkunde, 158(6), 553-63 | Language
1334 | Koletzko, B.,Schiess, S.,Brands, B.,Haile, G.,Demmelmair, H.,Kries, R.,Grote, V. (2010). [Infant feeding practice and later obesity risk. Indications for early metabolic programming] Bundesgesundheitsblatt, Gesundheitsforschung, Gesundheitsschutz, 53(7), 666-73 | Language
1335 | Koletzko, B.,Toschke, A. M.,Vignerova, J.,Osancova, K.,Von Kries, R. (2003). Does breast feeding protect against later overweight and obesity? Cesko-Slovenska Pediatrie, 58(1), 3-9 | Publication status
1336 | Koletzko, B.,von Kries, R. (2002). Are there long term protective effects of breast feeding against later obesity? Pediatria Wspolczesna, 4(3), 217-223 | Language
1337 | Koletzko, B.,Von Kries, R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Cachera, M. F. R.,Grote, V. (2009). Lower protein in infant formula is associated with lower weight up to age 2 y: A randomized clinical trial American Journal of Clinical Nutrition, 89(6), 1836-1845 | Intervention/exposure
1338 | Koletzko, B.,von, K. R.,Closa, R.,Escribano, J.,Scaglioni, S.,Giovannini, M.,Beyer, J.,Demmelmair, H.,Anton, B.,Gruszfeld, D.,Dobrzanska, A.,Sengier, A.,Langhendries, J. P.,Rolland Cachera, M. F.,Grote, V. (2009). Can infant feeding choices modulate later obesity risk? American journal of clinical nutrition, 89(5), 1502s-1508s | Study design
1339 | Koletzko, S.,Griffiths, A.,Corey, M.,Smith, C.,Sherman, P. (1991). Infant feeding practices and ulcerative colitis in childhood BMJ, 302(6792), 1580-1 | Outcome
1340 | Koletzko, S.,Sherman, P.,Corey, M.,Griffiths, A.,Smith, C. (1989). Role of infant feeding practices in development of Crohn’s disease in childhood BMJ, 298(6688), 1617-8 | Outcome
1341 | Koloski, N. A.,Jones, M.,Weltman, M.,Kalantar, J.,Bone, C.,Gowryshankar, A.,Walker, M. M.,Talley, N. J. (2015). Identification of early environmental risk factors for irritable bowel syndrome and dyspepsia Neurogastroenterol Motil, 27(9), 1317-25 | Outcome
1342 | Koopman, J. S.,Turkish, V. J.,Monto, A. S. (1985). Infant formulas and gastrointestinal illness Am J Public Health, 75(5), 477-80 | Outcome
1343 | Kosse, F. (2016). The Nutritional and Social Environment-Related Effects of Breastfeeding on Intelligence JAMA Pediatr, 170(2), 173-4 | Study design, Outcome
1344 | Kost, N. V.,Sokolov, O. Y.,Kurasova, O. B.,Dmitriev, A. D.,Tarakanova, J. N.,Gabaeva, M. V.,Zolotarev, Y. A.,Dadayan, A. K.,Grachev, S. A.,Korneeva, E. V.,Mikheeva, I. G.,Zozulya, A. A. (2009). Beta-casomorphins-7 in infants on different type of feeding and different levels of psychomotor development Peptides, 30(10), 1854-60 | Study design, Intervention/exposure
1345 | Koster, E. S.,Van der Ent, C. K.,Uiterwaal, C. S.,Verheij, T. J.,Raaijmakers, J. A.,Maitland-van der Zee, A. H. (2011). Asthma medication use in infancy: determinants related to prescription of drug therapy Fam Pract, 28(4), 377-84 | Intervention/exposure
1346 | Kostraba, J. N.,Cruickshanks, K. J.,Lawler-Heavner, J.,Jobim, L. F.,Rewers, M. J.,Gay, E. C.,Chase, H. P.,Klingensmith, G.,Hamman, R. F. (1993). Early exposure to cow’s milk and solid foods in infancy, genetic predisposition, and risk of IDDM Diabetes, 42(2), 288-95 | Outcome
1347 | Kostraba, J. N.,Dorman, J. S.,LaPorte, R. E.,Scott, F. W.,Steenkiste, A. R.,Gloninger, M.,Drash, A. L. (1992). Early infant diet and risk of IDDM in blacks and whites. A matched case-control study Diabetes Care, 15(5), 626-31 | Outcome
1348 | Krabbendam, L.,Bakker, E.,Hornstra, G.,van Os, J. (2007). Relationship between DHA status at birth and child problem behaviour at 7 years of age Prostaglandins Leukot Essent Fatty Acids, 76(1), 29-34 | Outcome
1349 | Kramer, M. S. (1981). Do breast-feeding and delayed introduction of solid foods protect against subsequent obesity? J Pediatr, 98(6), 883-7 | Outcome
1350 | Kramer, M. S. (1988). Infant feeding, infection, and public health Pediatrics, 81(1), 164-6 | Study design
1351 | Kramer, M. S. (2010). “Breast is best”: The evidence Early Hum Dev, 86(11), 729-32 | Outcome
1352 | Kramer, M. S.,Aboud, F.,Mironova, E.,Vanilovich, I.,Platt, R. W.,Matush, L.,Igumnov, S.,Fombonne, E.,Bogdanovich, N.,Ducruet, T.,Collet, J. P.,Chalmers, B.,Hodnett, E.,Davidovsky, S.,Skugarevsky, O.,Trofimovich, O.,Kozlova, L.,Shapiro, S. (2008). Breastfeeding and child cognitive development: new evidence from a large randomized trial Arch Gen Psychiatry, 65(5), 578-84 | Outcome
1353 | Kramer, M. S.,Barr, R. G.,Leduc, D. G.,Boisjoly, C.,McVey-White, L.,Pless, I. B. (1985). Determinants of weight and adiposity in the first year of life J Pediatr, 106(1), 10-4 | Outcome
1354 | Kramer, M. S.,Barr, R. G.,Pless, I. B. (1986). Determinants of weight and adiposity in early childhood Canadian Journal of Public Health, 77(SUPPL. 1), 98-103 | Outcome
1355 | Kramer, M. S.,Chalmers, B.,Hodnett, E. D.,Sevkovskaya, Z.,Dzikovich, I.,Shapiro, S.,Collet, J. P.,Vanilovich, I.,Mezen, I.,Ducruet, T.,Shishko, G.,Zubovich, V.,Mknuik, D.,Gluchanina, E.,Dombrovskiy, V.,Ustinovitch, A.,Kot, T.,Bogdanovich, N.,Ovchinikova, L.,Helsing, E. (2001). Promotion of breastfeeding intervation trial (PROBIT): A randomized trial in the Republic of Belarus Journal of the American Medical Association, 285(4), 413-420 | Outcome
1356 | Kramer, M. S.,Fombonne, E.,Igumnov, S.,Vanilovich, I.,Matush, L.,Mironova, E.,Bogdanovich, N.,Tremblay, R. E.,Chalmers, B.,Zhang, X.,Platt, R. W. (2008). Effects of prolonged and exclusive breastfeeding on child behavior and maternal adjustment: evidence from a large, randomized trial Pediatrics, 121(3), e435-40 | Outcome
1357 | Kramer, M. S.,Fombonne, E.,Matush, L.,Bogdanovich, N.,Dahhou, M.,Platt, R. W. (2011). Long-term behavioural consequences of infant feeding: the limits of observational studies Paediatr Perinat Epidemiol, 25(6), 500-6 | Outcome
1358 | Kramer, M. S.,Guo, T.,Platt, R. W.,Sevkovskaya, Z.,Dzikovich, I.,Collet, J. P.,Shapiro, S.,Chalmers, B.,Hodnett, E.,Vanilovich, I.,Mezen, I.,Ducruet, T.,Shishko, G.,Bogdanovich, N. (2003). Infant growth and health outcomes associated with 3 compared with 6 mo of exclusive breastfeeding Am J Clin Nutr, 78(2), 291-5 | Outcome
1359 | Kramer, M. S.,Guo, T.,Platt, R. W.,Shapiro, S.,Collet, J. P.,Chalmers, B.,Hodnett, E.,Sevkovskaya, Z.,Dzikovich, I.,Vanilovich, I. (2002). Breastfeeding and infant growth: biology or bias? Pediatrics, 110(2 Pt 1), 343-7 | Outcome
1360 | Kramer, M. S.,Guo, T.,Platt, R. W.,Vanilovich, I.,Sevkovskaya, Z.,Dzikovich, I.,Michaelsen, K. F.,Dewey, K. (2004). Feeding effects on growth during infancy J Pediatr, 145(5), 600-5 | Intervention/exposure
1361 | Kramer, M. S.,Martin, R. M.,Bogdanovich, N.,Vilchuk, K.,Dahhou, M.,Oken, E. (2014). Is restricted fetal growth associated with later adiposity? Observational analysis of a randomized trial Am J Clin Nutr, 100(1), 176-81 | Outcome
1362 | Kramer, M. S.,Matush, L.,Aboud, F.,Vanilovich, I.,Bogdanovich, N.,Mironova, E. (2007). Long-term child health effects of breastfeeding in developed countries: new evidence from the PROBIT trial [abstract] Journal of human lactation, 23(1), 90 | Study design
1363 | Kramer, M. S.,Matush, L.,Bogdanovich, N.,Aboud, F.,Mazer, B.,Fombonne, E.,Collet, J. P.,Hodnett, E.,Mironova, E.,Igumnov, S.,Chalmers, B.,Dahhou, M.,Platt, R. W. (2009). Health and development outcomes in 6.5-y-old children breastfed exclusively for 3 or 6 mo Am J Clin Nutr, 90(4), 1070-4 | Outcome
1364 | Kramer, M. S.,Matush, L.,Bogdanovich, N.,Dahhou, M.,Platt, R. W.,Mazer, B. (2009). The low prevalence of allergic disease in Eastern Europe: are risk factors consistent with the hygiene hypothesis? Clin Exp Allergy, 39(5), 708-16 | Intervention/exposure
1365 | Kramer, M. S.,Matush, L.,Vanilovich, I.,Platt, R. W.,Bogdanovich, N.,Sevkovskaya, Z.,Dzikovich, I.,Shishko, G.,Collet, J. P.,Martin, R. M.,Davey Smith, G.,Gillman, M. W.,Chalmers, B.,Hodnett, E.,Shapiro, S. (2007). Effects of prolonged and exclusive breastfeeding on child height, weight, adiposity, and blood pressure at age 6.5 y: evidence from a large randomized trial Am J Clin Nutr, 86(6), 1717-21 | Outcome
1366 | Kramer, M. S.,Matush, L.,Vanilovich, I.,Platt, R. W.,Bogdanovich, N.,Sevkovskaya, Z.,Dzikovich, I.,Shishko, G.,Collet, J. P.,Martin, R. M.,Smith, G. D.,Gillman, M. W.,Chalmers, B.,Hodnett, E.,Shapiro, S. (2009). A randomized breast-feeding promotion intervention did not reduce child obesity in Belarus J Nutr, 139(2), 417S-21S | Study design
1367 | Kramer, M. S.,Matush, L.,Vanilovich, I.,Platt, R.,Bogdanovich, N.,Sevkovskaya, Z.,Dzikovich, I.,Shishko, G.,Mazer, B. (2007). Effect of prolonged and exclusive breast feeding on risk of allergy and asthma: cluster randomised trial BMJ, 335(7624), 815 | Outcome
1368 | Kramer, M. S.,Moodie, E. E.,Dahhou, M.,Platt, R. W. (2011). Breastfeeding and infant size: evidence of reverse causality Am J Epidemiol, 173(9), 978-83 | Intervention/exposure
1369 | Kramer, M. S.,Moodie, E. E.,Platt, R. W. (2012). Infant feeding and growth: can we answer the causal question? Epidemiology, 23(6), 790-4 | Study design
1370 | Kramer, M. S.,Moroz, B. (1981). Do breast-feeding and delayed introduction of solid foods protect against subsequent atopic eczema? J Pediatr, 98(4), 546-50 | Study design
1371 | Kramer, M. S.,Vanilovich, I.,Matush, L.,Bogdanovich, N.,Zhang, X.,Shishko, G.,Muller-Bolla, M.,Platt, R. W. (2007). The effect of prolonged and exclusive breast-feeding on dental caries in early school-age children. New evidence from a large randomized trial Caries Res, 41(6), 484-8 | Outcome
1372 | Kramer, M.,Matush, L.,Vanilovich, I.,Platt, R.,Mazer, B. (2006). Does breastfeeding help prevent asthma and allergy? Evidence from a randomized trial in Belarus American journal of epidemiology, 163(Suppl 11), S85 | Publication status
1373 | Kramer,,M, S.,Matush,,L,,Vanilovich,,I,,Platt,,R, W.,Bogdanovich,,N,,Sevkovskaya,,Z,,Dzikovich,,I,,Shishko,,G,,Collet,,J, P.,Martin,,R, M.,Davey, Smith,G,,Gillman,,M, W.,Chalmers,,B,,Hodnett,,E,,Shapiro,,S, (2007). Effects of prolonged and exclusive breastfeeding on child height, weight, adiposity, and blood pressure at age 6.5 y: evidence from a large randomized trial Am J Clin Nutr, 86(6), 1717-21 | Duplicate
1374 | Kraus, J. F.,Greenland, S.,Bulterys, M. (1989). Risk factors for sudden infant death syndrome in the US Collaborative Perinatal Project Int J Epidemiol, 18(1), 113-20 | Outcome
1375 | Kravetz, R. E. (2003). Infant nursing bottle Am J Gastroenterol, 98(7), 1640 | Study design, Outcome
1376 | Krebs, N. F.,Hambidge, K. M.,Westcott, J. E.,Miller, L. V.,Sian, L.,Bell, M.,Grunwald, G. (2003). Exchangeable zinc pool size in infants is related to key variables of zinc homeostasis J Nutr, 133(5 Suppl 1), 1498S-501S | Study design, Size of study groups
1377 | Krebs, N. F.,Reidinger, C. J.,Robertson, A. D.,Hambidge, K. M. (1994). Growth and intakes of energy and zinc in infants fed human milk J Pediatr, 124(1), 32-9 | Intervention/exposure
1378 | Krebs, N. F.,Reidinger, C.,Westcott, J.,Miller, L. V.,Fennessey, P. V.,Hambidge, K. M. (1994). Whole body zinc metabolism in full-term breasted and formula fed infants Adv Exp Med Biol, 352(#issue#), 223-6 | Study design, Size of study groups
1379 | Krebs, N. F.,Westcott, J. E.,Culbertson, D. L.,Sian, L.,Miller, L. V.,Hambidge, K. M. (2012). Comparison of complementary feeding strategies to meet zinc requirements of older breastfed infants Am J Clin Nutr, 96(1), 30-5 | Intervention/exposure
1380 | Krenz-Niedbala, M.,Puch, E. A.,Koscinski, K. (2011). Season of birth and subsequent body size: the potential role of prenatal vitamin D Am J Hum Biol, 23(2), 190-200 | Study design
1381 | Krishna, L. M. (1980). Breast feeding and development Public Health, 94(1), 21-4 | Study design
1382 | Kristiansen, A. L.,Laugsand Lillegaard, I. T.,Frost Andersen, L. (2013). Effect of changes in a food frequency questionnaire: comparing data from two national dietary survey instruments among 12-month-old infants BMC Public Health, 13(#issue#), 680 | Study design, Intervention/exposure
1383 | Krous, H. F.,Chadwick, A. E.,Stanley, C. (2005). Delayed infant death following catastrophic deterioration during breast-feeding J Paediatr Child Health, 41(4), 215-7 | Study design
1384 | Kucukcongar A,Oguz A,Pinarli FG,Karadeniz C,Okur A,Kaya Z,Celik B (2015). Breastfeeding and Childhood Cancer: Is Breastfeeding Preventative to Childhood Cancer? Pediatr Hematol Oncol, 32(#issue#), 374-81 | Outcome
1385 | Küçükçongar, A.,Oʇuz, A.,Pinarli, F. G.,Karadeniz, C.,Okur, A.,Kaya, Z.,Çelik, B. (2015). Breastfeeding and Childhood Cancer: Is Breastfeeding Preventative to Childhood Cancer? Pediatric Hematology and Oncology, 32(6), 374-381 | Outcome, Duplicate
1386 | Kucur, C.,Simsek, E.,Kuduban, O.,Ozbay, I. (2015). Prevalence of and risk factors for otitis media with effusion in primary school children: case control study in Erzurum, Turkey Turk J Pediatr, 57(3), 230-5 | Study design, Outcome
1387 | Kuhn, T.,Kroke, A.,Remer, T.,Schonau, E.,Buyken, A. E. (2014). Is breastfeeding related to bone properties? A longitudinal analysis of associations between breastfeeding duration and pQCT parameters in children and adolescents Matern Child Nutr, 10(4), 642-9 | Intervention/exposure
1388 | Kuhnisch, J.,Mach, D.,Thiering, E.,Brockow, I.,Hoffmann, U.,Neumann, C.,Heinrich-Weltzien, R.,Bauer, C. P.,Berdel, D.,von Berg, A.,Koletzko, S.,Garcia-Godoy, F.,Hickel, R.,Heinrich, J. (2014). Respiratory diseases are associated with molar-incisor hypomineralizations Swiss Dent J, 124(3), 286-93 | Outcome
1389 | Kuiper, S.,Muris, J. W.,Dompeling, E.,Kester, A. D.,Wesseling, G.,Knottnerus, J. A.,van Schayck, C. P. (2007). Interactive effect of family history and environmental factors on respiratory tract-related morbidity in infancy J Allergy Clin Immunol, 120(2), 388-95 | Outcome
1390 | Kukkonen, A. K.,Savilahti, E. M.,Haahtela, T.,Savilahti, E.,Kuitunen, M. (2011). Ovalbumin-specific immunoglobulins A and G levels at age 2 years are associated with the occurrence of atopic disorders Clin Exp Allergy, 41(10), 1414-21 | Intervention/exposure
1391 | Kull, I.,Almqvist, C.,Lilja, G.,Pershagen, G.,Wickman, M. (2004). Breast-feeding reduces the risk of asthma during the first 4 years of life J Allergy Clin Immunol, 114(4), 755-60 | Outcome
1392 | Kull, I.,Bohme, M.,Wahlgren, C. F.,Nordvall, L.,Pershagen, G.,Wickman, M. (2005). Breast-feeding reduces the risk for childhood eczema J Allergy Clin Immunol, 116(3), 657-61 | Intervention/exposure
1393 | Kull, I.,Melen, E.,Alm, J.,Hallberg, J.,Svartengren, M.,van Hage, M.,Pershagen, G.,Wickman, M.,Bergstrom, A. (2010). Breast-feeding in relation to asthma, lung function, and sensitization in young schoolchildren J Allergy Clin Immunol, 125(5), 1013-9 | Intervention/exposure
1394 | Kull, I.,Wickman, M.,Lilja, G.,Nordvall, S. L.,Pershagen, G. (2002). Breast feeding and allergic diseases in infants-a prospective birth cohort study Arch Dis Child, 87(6), 478-81 | Outcome
1395 | Kumar, A. (1985). Breast feeding versus bottle feeding J Indian Med Assoc, 83(10), 365-6 | Study design
1396 | Kumar, V.,Sharma, S.,Khanna, P.,Vanaja, K. (1981). Breast vs bottle feeding-impact on growth in urban infants Indian J Pediatr, 48(392), 271-5 | Country
1397 | Kumari, S.,Jain, P.,Arora, U.,Pruthi, R. K. (1982). Growth of breast fed infants. A longitudinal study Indian Pediatr, 19(12), 963-8 | Country
1398 | Kumari, S.,Pruthi, P. K.,Mehra, R.,Sehgal, H. (1985). Breast feeding: physical growth during infancy Indian J Pediatr, 52(414), 73-7 | Country
1399 | Kuperberg, K.,Evers, S. (2006). Feeding patterns and weight among First Nations children Can J Diet Pract Res, 67(2), 79-84 | Intervention/exposure
1400 | Kupers, L. K.,L’Abee, C.,Bocca, G.,Stolk, R. P.,Sauer, P. J.,Corpeleijn, E. (2015). Determinants of Weight Gain during the First Two Years of Life--The GECKO Drenthe Birth Cohort PLoS One, 10(7), e0133326 | Intervention/exposure
1401 | Kuriakose, J. R. (2010). Nutritional status and feeding practices of infants Nurs J India, 101(8), 184-6 | Country
1402 | Kurugol, Z.,Coker, M.,Coker, C.,Egemen, A.,Ersoz, B. (1997). Comparison of growth, serum prealbumin, transferrin, IgG and amino acids of term infants fed breast mild or formula Turk J Pediatr, 39(2), 195-202 | Size of study groups
1403 | Kurugol, Z.,Geylani, S.,Karaca, Y.,Umay, F.,Erensoy, S.,Vardar, F.,Bak, M.,Yaprak, I.,Ozkinay, F.,Ozkinay, C. (2003). Rotavirus gastroenteritis among children under five years of age in Izmir, Turkey Turk J Pediatr, 45(4), 290-4 | Participant health, Intervention/exposure
1404 | Kurugöl, Z.,Geylani, S.,Karaca, Y.,Umay, F.,Erensoy, S.,Vardar, F.,Bak, M.,Yaprak, I.,Özkinay, F.,Özkinay, C. (2003). Rotavirus gastroenteritis among children under five years of age in ˙Izmir, Turkey Turkish Journal of Pediatrics, 45(4), 290-294 | Study design, Intervention/exposure
1405 | Kurukulaaratchy, R. J.,Matthews, S.,Arshad, S. H. (2006). Relationship between childhood atopy and wheeze: what mediates wheezing in atopic phenotypes? Ann Allergy Asthma Immunol, 97(1), 84-91 | Intervention/exposure
1406 | Kurzewski, K.,Gardner, J. M. (2005). Breastfeeding patterns among six-week-old term infants at the University Hospital of the West Indies West Indian Med J, 54(1), 28-33 | Study design
1407 | Kusel, M. M.,Holt, P. G.,de Klerk, N.,Sly, P. D. (2005). Support for 2 variants of eczema J Allergy Clin Immunol, 116(5), 1067-72 | Outcome
1408 | Kusunoki, T.,Morimoto, T.,Nishikomori, R.,Yasumi, T.,Heike, T.,Mukaida, K.,Fujii, T.,Nakahata, T. (2010). Breastfeeding and the prevalence of allergic diseases in schoolchildren: Does reverse causation matter? Pediatric Allergy and Immunology, 21(1 PART I), 60-66 | Study design
1409 | Kuyucu, S.,Saraclar, Y.,Tuncer, A.,Sackesen, C.,Adalioglu, G.,Sumbuloglu, V.,Sekerel, B. E. (2004). Determinants of atopic sensitization in Turkish school children: effects of pre- and post-natal events and maternal atopy Pediatr Allergy Immunol, 15(1), 62-71 | Study design
1410 | Kvaavik, E.,Tell, G. S.,Klepp, K. I. (2005). Surveys of Norwegian youth indicated that breast feeding reduced subsequent risk of obesity J Clin Epidemiol, 58(8), 849-55 | Outcome
1411 | Kwan, M. L.,Buffler, P. A.,Wiemels, J. L.,Metayer, C.,Selvin, S.,Ducore, J. M.,Block, G. (2005). Breastfeeding patterns and risk of childhood acute lymphoblastic leukaemia Br J Cancer, 93(3), 379-84 | Outcome
1412 | Kwok, M. K.,Leung, G. M.,Schooling, C. M. (2013). Breast feeding and early adolescent behaviour, self-esteem and depression: Hong Kong’s ‘Children of 1997’ birth cohort Arch Dis Child, 98(11), 887-94 | Outcome
1413 | Kwok, M. K.,Leung, G. M.,Schooling, C. M. (2013). Breastfeeding and adolescent blood pressure: evidence from Hong Kong’s “Children of 1997” Birth Cohort Am J Epidemiol, 178(6), 928-36 | Outcome
1414 | Kwok, M. K.,Schooling, C. M.,Lam, T. H.,Leung, G. M. (2010). Does breastfeeding protect against childhood overweight? Hong Kong’s ‘Children of 1997’ birth cohort Int J Epidemiol, 39(1), 297-305 | Outcome
1415 | Kyvik, K. O.,Green, A.,Svendsen, A.,Mortensen, K. (1992). Breast feeding and the development of type 1 diabetes mellitus Diabet Med, 9(3), 233-5 | Outcome
1416 | Labayen, I.,Ortega, F. B.,Ruiz, J. R.,Rodriguez, G.,Jiménez-Pavón, D.,España-Romero, V.,Widhalm, K.,Gottrand, F.,Moreno, L. A. (2015). Breastfeeding attenuates the effect of low birthweight on abdominal adiposity in adolescents: The HELENA study Maternal and Child Nutrition, 11(4), 1036-1040 | Study design
1417 | Labayen, I.,Ruiz, J. R.,Ortega, F. B.,Loit, H. M.,Harro, J.,Villa, I.,Veidebaum, T.,Sjostrom, M. (2012). Exclusive breastfeeding duration and cardiorespiratory fitness in children and adolescents Am J Clin Nutr, 95(2), 498-505 | Study design
1418 | Labbok, M. H. (1985). Consequences of breast-feeding for mother and child J Biosoc Sci Suppl, 9(#issue#), 43-54 | Study design
1419 | Ladd GA (1986). Merlin’s molars Cal, 49(#issue#), 14-5, 31 | Study design
1420 | Laditan, A. A. (1983). Bilateral genu vara in childhood Cent Afr J Med, 29(11), 219-23 | Country, Outcome
1421 | Ladomenou, F.,Kafatos, A.,Galanakis, E. (2009). Environmental tobacco smoke exposure as a risk factor for infections in infancy Acta Paediatr, 98(7), 1137-41 | Intervention/exposure
1422 | Ladomenou, F.,Kafatos, A.,Tselentis, Y.,Galanakis, E. (2010). Predisposing factors for acute otitis media in infancy J Infect, 61(1), 49-53 | Outcome
1423 | Ladomenou, F.,Moschandreas, J.,Kafatos, A.,Tselentis, Y.,Galanakis, E. (2010). Protective effect of exclusive breastfeeding against infections during infancy: a prospective study Arch Dis Child, 95(12), 1004-8 | Outcome
1424 | Lakhani SA,Chaudhri T,Jansen AA (1983). Human milk and milk formulas for infant feeding East Afr Med J, 60(#issue#), 181-5 | Study design
1425 | Lakshman, R.,Whittle, F.,Hardeman, W.,Suhrcke, M.,Wilson, E.,Griffin, S.,Ong, K. K. (2015). Effectiveness of a behavioural intervention to prevent excessive weight gain during infancy (The Baby Milk Trial): study protocol for a randomised controlled trial Trials, 16(1), 442 | Study design, Intervention/exposure
1426 | Lamb, M. M.,Dabelea, D.,Yin, X.,Ogden, L. G.,Klingensmith, G. J.,Rewers, M.,Norris, J. M. (2010). Early-life predictors of higher body mass index in healthy children Ann Nutr Metab, 56(1), 16-22 | Outcome
1427 | Lamb, M. M.,Simpson, M. D.,Seifert, J.,Scott, F. W.,Rewers, M.,Norris, J. M. (2013). The association between IgG4 antibodies to dietary factors, islet autoimmunity and type 1 diabetes: the Diabetes Autoimmunity Study in the Young PLoS One, 8(2), e57936 | Size of study groups, Outcome
1428 | Lamichhane, A. P.,Crandell, J. L.,Jaacks, L. M.,Couch, S. C.,Lawrence, J. M.,Mayer-Davis, E. J. (2015). Longitudinal associations of nutritional factors with glycated hemoglobin in youth with type 1 diabetes: the SEARCH Nutrition Ancillary Study Am J Clin Nutr, 101(6), 1278-85 | Participant health, Outcomes
1429 | Lanari, M.,Adorni, F.,Silvestri, M.,Coscia, A.,Musicco, M. (2011). The multicenter Italian birth cohort study on incidence and determinants of lower respiratory tract infection hospitalization in infants at 33 weeks GA or more: preliminary results Early Hum Dev, 87 Suppl 1(#issue#), S43-6 | Intervention/exposure
1430 | Lanari, M.,Prinelli, F.,Adorni, F.,Di Santo, S.,Faldella, G.,Silvestri, M.,Musicco, M. (2013). Maternal milk protects infants against bronchiolitis during the first year of life. Results from an Italian cohort of newborns Early Hum Dev, 89 Suppl 1(#issue#), S51-7 | Outcome
1431 | Lanari, M.,Prinelli, F.,Adorni, F.,Di Santo, S.,Vandini, S.,Silvestri, M.,Musicco, M. (2015). Risk factors for bronchiolitis hospitalization during the first year of life in a multicenter Italian birth cohort Ital J Pediatr, 41(#issue#), 40 | Outcome
1432 | Lancashire, R. J.,Sorahan, T. (2003). Breastfeeding and childhood cancer risks: OSCC data Br J Cancer, 88(7), 1035-7 | Outcome
1433 | Landaas, S.,Skrede, S.,Steen, J. A. (1981). The levels of serum enzymes, plasma proteins and lipids in normal infants and small children J Clin Chem Clin Biochem, 19(10), 1075-80 | Study design
1434 | Lande, B.,Andersen, L. F.,Henriksen, T.,Baerug, A.,Johansson, L.,Trygg, K. U.,Bjorneboe, G. E.,Veierod, M. B. (2005). Relations between high ponderal index at birth, feeding practices and body mass index in infancy Eur J Clin Nutr, 59(11), 1241-9 | Outcome
1435 | Lane, B. J.,Sellen, V. (1986). Bottle caries: a nursing responsibility Can J Public Health, 77(2), 128-30 | Study design
1436 | Lane, D. M.,McConathy, W. J. (1986). Changes in the serum lipids and apolipoproteins in the first four weeks of life Pediatr Res, 20(4), 332-7 | Size of study groups
1437 | Langeland, T. (1983). A clinical and immunological study of allergy to hen’s egg white. I. A clinical study of egg allergy Clin Allergy, 13(4), 371-82 | Intervention/exposure, Outcome
1438 | Langman, M. J. (1986). Can epidemiology help us prevent celiac disease? Gastroenterology, 90(2), 489-91 | Study design
1439 | Langnase, K.,Mast, M.,Danielzik, S.,Spethmann, C.,Muller, M. J. (2003). Socioeconomic gradients in body weight of German children reverse direction between the ages of 2 and 6 years J Nutr, 133(3), 789-96 | Outcome
1440 | Lanting, C. I.,Fidler, V.,Huisman, M.,Touwen, B. C.,Boersma, E. R. (1994). Neurological differences between 9-year-old children fed breast-milk or formula-milk as babies Lancet, 344(8933), 1319-22 | Intervention/exposure
1441 | Lanting, C. I.,Patandin, S.,Weisglas-Kuperus, N.,Touwen, B. C.,Boersma, E. R. (1998). Breastfeeding and neurological outcome at 42 months Acta Paediatr, 87(12), 1224-9 | Outcome
1442 | Laohaviranit L (1985). Milk and health J Med Assoc Thai, 68(#issue#), 326-9 | Study design
1443 | Lapillonne, A.,Brossard, N.,Claris, O.,Reygrobellet, B.,Salle, B. L. (2000). Erythrocyte fatty acid composition in term infants fed human milk or a formula enriched with a low eicosapentanoic acid fish oil for 4 months Eur J Pediatr, 159(1-2), 49-53 | Intervention/exposure, Size of study groups
1444 | Lapinleimu, H.,Vukari, J.,Nunikoski, H.,Tuominen, J.,Ronnemaa, T.,Valimaki, I.,Marniemi, J.,Jokinen, E.,Ehnholm, C.,Simell, O. (1997). Impact of gender, apolipoprotein E phenotypes, and diet on serum lipids and lipoproteins in infancy J Pediatr, 131(6), 825-32 | Intervention/exposure
1445 | Larsson, E. (2001). Sucking, chewing, and feeding habits and the development of crossbite: a longitudinal study of girls from birth to 3 years of age Angle Orthod, 71(2), 116-9 | Intervention/exposure, Outcome
1446 | Larsson, J.,Aurelius, G.,Nordberg, L.,Rydelius, P.,Zetterström, R. (1999). The role of cumulative observations in identifying children in need of health promotion…including commentary by Glascoe FP Ambulatory Child Health, 5(3), 209-217 9p | Outcome
1447 | Larsson, M.,Hagerhed-Engman, L.,Sigsgaard, T.,Janson, S.,Sundell, J.,Bornehag, C. G. (2008). Incidence rates of asthma, rhinitis and eczema symptoms and influential factors in young children in Sweden Acta Paediatr, 97(9), 1210-5 | Outcome
1448 | Lasekan, J. B.,Ostrom, K. M.,Jacobs, J. R.,Blatter, M. M.,Ndife, L. I.,Gooch, Iii W. M.,Cho, S. (1999). Growth of newborn, term infants fed soy formulas for 1 year Clinical Pediatrics, 38(10), 563-571 | Outcome
1449 | Laskey, M. A.,de Bono, S.,Smith, E. C.,Prentice, A. (2007). Influence of birth weight and early diet on peripheral bone in premenopausal Cambridge women: a pQCT study J Musculoskelet Neuronal Interact, 7(1), 83 | Study design
1450 | Lau, Y. L.,Karlberg, J.,Yeung, C. Y. (1995). Prevalence of and factors associated with childhood asthma in Hong Kong Acta Paediatr, 84(7), 820-2 | Study design
1451 | Laubereau, B.,Brockow, I.,Zirngibl, A.,Koletzko, S.,Gruebl, A.,von Berg, A.,Filipiak-Pittroff, B.,Berdel, D.,Bauer, C. P.,Reinhardt, D.,Heinrich, J.,Wichmann, H. E. (2004). Effect of breast-feeding on the development of atopic dermatitis during the first 3 years of life--results from the GINI-birth cohort study J Pediatr, 144(5), 602-7 | Intervention/exposure
1452 | Lauer, J. A.,Betran, A. P.,Barros, A. J.,de Onis, M. (2006). Deaths and years of life lost due to suboptimal breast-feeding among children in the developing world: a global ecological risk assessment Public Health Nutr, 9(6), 673-85 | Country, Study design
1453 | Lauritzen, L.,Jorgensen, M. H.,Mikkelsen, T. B.,Skovgaard l, M.,Straarup, E. M.,Olsen, S. F.,Hoy, C. E.,Michaelsen, K. F. (2004). Maternal fish oil supplementation in lactation: effect on visual acuity and n-3 fatty acid content of infant erythrocytes Lipids, 39(3), 195-206 | Intervention/exposure
1454 | Lauver, M. A.,Hizon, L.,Bulla, A.,Connell, C.,Wagoner, B. (1981). Infant feeding practices: the effect on six month weight J Kans Med Soc, 82(9), 403-6 | Size of study groups
1455 | Lauzon-Guillain, Bd,Wijndaele, K.,Clark, M.,Acerini, C. L.,Hughes, I. A.,Dunger, D. B.,Wells, J. C.,Ong, K. K. (2012). Breastfeeding and infant temperament at age three months PLoS One, 7(1), e29326 | Study design
1456 | Lawlor, D. A.,Najman, J. M.,Batty, G. D.,O’Callaghan, M. J.,Williams, G. M.,Bor, W. (2006). Early life predictors of childhood intelligence: findings from the Mater-University study of pregnancy and its outcomes Paediatr Perinat Epidemiol, 20(2), 148-62 | Outcome
1457 | Lawlor, D. A.,Najman, J. M.,Sterne, J.,Williams, G. M.,Ebrahim, S.,Davey Smith, G. (2004). Associations of parental, birth, and early life characteristics with systolic blood pressure at 5 years of age: findings from the Mater-University study of pregnancy and its outcomes Circulation, 110(16), 2417-23 | Intervention/exposure
1458 | Lawlor, D. A.,Riddoch, C. J.,Page, A. S.,Andersen, L. B.,Wedderkopp, N.,Harro, M.,Stansbie, D.,Smith, G. D. (2005). Infant feeding and components of the metabolic syndrome: findings from the European Youth Heart Study Arch Dis Child, 90(6), 582-8 | Study design, Intervention/exposure
1459 | Lawrence, R. A. (1991). Breast-feeding trends: a cause for action Pediatrics, 88(4), 867-8 | Study design
1460 | Lawrence, R. A. (1992). Can we expect greater intelligence from human milk feedings? Birth, 19(2), 105-6 | Study design
1461 | Lawrence, R. A. (2001). Promotion of Breastfeeding Intervention Trial (PROBIT) a randomized trial in the Republic of Belarus J Pediatr, 139(1), 164-5 | Study design
1462 | Layte, R.,Bennett, A.,McCrory, C.,Kearney, J. (2014). Social class variation in the predictors of rapid growth in infancy and obesity at age 3 years Int J Obes (Lond), 38(1), 82-90 | Outcome
1463 | Lazerov, J.,Ervin, C. (2011). Promoting breastfeeding: breastfeeding and population health Breastfeed Med, 6(#issue#), 305-6 | Study design
1464 | Leary SD, Lawlor DA, Davey Smith G, Brion MJ, Ness AR. (2015). Behavioural early-life exposures and body composition at age 15 years Nutrition and Diabetes, 5(2), e150 | Outcome
1465 | Lee, B. (1995). Breastfeeding J R Soc Med, 88(9), 537p-538p | Study design
1466 | Lee, H. A.,Kim, Y. J.,Lee, H.,Gwak, H. S.,Hong, Y. S.,Kim, H. S.,Park, E. A.,Cho, S. J.,Ha, E. H.,Park, H. (2015). The preventive effect of breast-feeding for longer than 6 months on early pubertal development among children aged 7-9 years in Korea Public Health Nutr, #volume#(#issue#), 1-8 | Study design, Intervention/exposure
1467 | Lee, L. C.,Pratt, C. A.,DeLaski-Smith, D.,Karabenick, S. A. (1999). The growth patterns of American-born Chinese infants Nutrition Research, 19(5), 697-708 | Size of study groups, Intervention/exposure
1468 | Leeson, C. P.,Kattenhorn, M.,Deanfield, J. E.,Lucas, A. (2001). Duration of breast feeding and arterial distensibility in early adult life: population based study BMJ, 322(7287), 643-7 | Study design
1469 | Legovic, M.,Ostric, L. (1991). The effects of feeding methods on the growth of the jaws in infants ASDC J Dent Child, 58(3), 253-5 | Study design
1470 | Lemons PK,Kochanczyk M,Lemons JA (1980). Breast-feeding the newborn J Indiana State Med Assoc, 73(#issue#), 373-8 | Study design
1471 | Lenguerrand, E.,Harding, S. (2010). P46 Ethnic differences in pace of growth between birth and 5 years: results from the millennium cohort study Journal of Epidemiology & Community Health, 64(#issue#), A51-A51 1p | Publication status
1472 | Leonard, W. R.,Dewalt, K. M.,Stansbury, J. P.,McCaston, M. K. (2000). Influence of dietary quality on the growth of highland and coastal Ecuadorian children Am J Hum Biol, 12(6), 825-837 | Outcome
1473 | Lerman, Y.,Slepon, R.,Cohen, D. (1994). Epidemiology of acute diarrheal diseases in children in a high standard of living rural settlement in Israel Pediatr Infect Dis J, 13(2), 116-22 | Study design
1474 | Leung, E. Y.,Au, K. Y.,Cheng, S. S.,Kok, S. Y.,Lui, H. K.,Wong, W. C. (2006). Practice of breastfeeding and factors that affect breastfeeding in Hong Kong Hong Kong Med J, 12(6), 432-6 | Outcome
1475 | Leung, G. M.,Lam, T. H.,Ho, L. M.,Lau, Y. L. (2005). Health consequences of breast-feeding: doctors’ visits and hospitalizations during the first 18 months of life in Hong Kong Chinese infants Epidemiology, 16(3), 328-35 | Outcome
1476 | Leung, J. Y.,Kwok, M. K.,Leung, G. M.,Schooling, C. M. (2015). Breastfeeding and childhood hospitalizations for asthma and other wheezing disorders Ann Epidemiol, #volume#(#issue#), #Pages# | Outcome
1477 | Leung, S. S. F.,Davies, D. P.,Lui, S.,Lo, L.,Yuen, P.,Swaminathan, R. (1988). Iron deficiency is uncommon in healthy Hong Kong infants at 18 months Journal of Tropical Pediatrics, 34(3), 100-103 | Intervention/exposure, Outcome
1478 | Leung, S. S.,Peng, C. X.,Xu, Y. Y.,Liu, K. M.,Quan, X. J.,Lui, S.,Davies, D. P. (1994). Comparative study of growth of Chinese infants: Hong Kong versus Guangzhou J Trop Pediatr, 40(3), 166-71 | Intervention/exposure
1479 | Leung, S.,Davies, D. P. (1994). Infant feeding and growth of Chinese infants: birth to 2 years Paediatr Perinat Epidemiol, 8(3), 301-13 | Intervention/exposure
1480 | Leventakou, V.,Roumeliotaki, T.,Koutra, K.,Vassilaki, M.,Mantzouranis, E.,Bitsios, P.,Kogevinas, M.,Chatzi, L. (2015). Breastfeeding duration and cognitive, language and motor development at 18 months of age: Rhea mother-child cohort in Crete, Greece J Epidemiol Community Health, 69(3), 232-9 | Outcome
1481 | Leventhal, J. M.,Shapiro, E. D.,Aten, C. B.,Berg, A. T.,Egerter, S. A. (1986). Does breast-feeding protect against infections in infants less than 3 months of age? Pediatrics, 78(5), 896-903 | Outcome
1482 | Lever, R. (2001). The role of food in atopic eczema J Am Acad Dermatol, 45(1 Suppl), S57-60 | Study design
1483 | Levine, O. S.,Farley, M.,Harrison, L. H.,Lefkowitz, L.,McGeer, A.,Schwartz, B. (1999). Risk factors for invasive pneumococcal disease in children: a population-based case-control study in North America Pediatrics, 103(3), E28 | Study design, Intervention/exposure
1484 | Lewando-Hundt, G.,Forman, M. R. (1997). Autonomy, access and care: a study of Palestinian Bedouin of the Negev of Israel Social Sciences in Health, 3(2), 83-95 13p | Intervention/exposure, Outcome
1485 | Lewis, J. K. Anderson M. Willeitner A. (2011). Powdered Versus Liquid Human Milk Fortifier: A Blinded, Randomized, Controlled Trial Pediatric Academic Societies Annual Meeting, #volume#(#issue#), #Pages# | Publication status
1486 | Lewis, S.,Butland, B.,Strachan, D.,Bynner, J.,Richards, D.,Butler, N.,Britton, J. (1996). Study of the aetiology of wheezing illness at age 16 in two national British birth cohorts Thorax, 51(7), 670-6 | Study design, Intervention/exposure
1487 | L’Hoir, M. P.,Engelberts, A. C.,van Well, G. T.,Damste, P. H.,Idema, N. K.,Westers, P.,Mellenbergh, G. J.,Wolters, W. H.,Huber, J. (1999). Dummy use, thumb sucking, mouth breathing and cot death Eur J Pediatr, 158(11), 896-901 | Outcome
1488 | l’Hoir, M. P.,Engelberts, A. C.,van Well, G. T.,Westers, P.,Mellenbergh, G. J.,Wolters, W. H.,Huber, J. (1998). Case-control study of current validity of previously described risk factors for SIDS in The Netherlands Arch Dis Child, 79(5), 386-93 | Outcome
1489 | Li, C.,Goran, M. I.,Kaur, H.,Nollen, N.,Ahluwalia, J. S. (2007). Developmental trajectories of overweight during childhood: role of early life factors Obesity (Silver Spring), 15(3), 760-71 | Outcome
1490 | Li, C.,Kaur, H.,Choi, W. S.,Huang, T. T.,Lee, R. E.,Ahluwalia, J. S. (2005). Additive interactions of maternal prepregnancy BMI and breast-feeding on childhood overweight Obes Res, 13(2), 362-71 | Outcome
1491 | Li, J.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M.,Pivik, R. T. (2010). Cortical responses to speech sounds in 3- and 6-month-old infants fed breast milk, milk formula, or soy formula Dev Neuropsychol, 35(6), 762-84 | Outcome
1492 | Li, L.,Kleinman, K.,Gillman, M. W. (2014). A comparison of confounding adjustment methods with an application to early life determinants of childhood obesity J Dev Orig Health Dis, 5(6), 435-47 | Study design, Intervention/exposure
1493 | Li, L.,Manor, O.,Power, C. (2004). Early environment and child-to-adult growth trajectories in the 1958 British birth cohort Am J Clin Nutr, 80(1), 185-92 | Intervention/exposure
1494 | Li, L.,Power, C. (2004). Influences on childhood height: comparing two generations in the 1958 British birth cohort Int J Epidemiol, 33(6), 1320-8 | Intervention/exposure
1495 | Li, N.,Strobino, D.,Ahmed, S.,Minkovitz, C. S. (2011). Is there a healthy foreign born effect for childhood obesity in the United States? Matern Child Health J, 15(3), 310-23 | Outcome
1496 | Li, R.,Dee, D.,Li, C. M.,Hoffman, H. J.,Grummer-Strawn, L. M. (2014). Breastfeeding and risk of infections at 6 years Pediatrics, 134 Suppl 1(#issue#), S13-20 | Outcome
1497 | Li, R.,Fein, S. B.,Grummer-Strawn, L. M. (2008). Association of breastfeeding intensity and bottle-emptying behaviors at early infancy with infants’ risk for excess weight at late infancy Pediatrics, 122 Suppl 2(#issue#), S77-84 | Outcome
1498 | Li, R.,Fein, S. B.,Grummer-Strawn, L. M. (2010). Do infants fed from bottles lack self-regulation of milk intake compared with directly breastfed infants? Pediatrics, 125(6), e1386-93 | Outcome
1499 | Li, R.,Magadia, J.,Fein, S. B.,Grummer-Strawn, L. M. (2012). Risk of bottle-feeding for rapid weight gain during the first year of life Arch Pediatr Adolesc Med, 166(5), 431-6 | Outcome
1500 | Li, S. C.,Kuo, S. C.,Hsu, Y. Y.,Lin, S. J.,Chen, P. C.,Chen, Y. C. (2010). Effect of Breastfeeding Duration on Infant Growth Until 18 Months of Age: A National Birth Cohort Study Journal of Experimental and Clinical Medicine, 2(4), 165-172 | Outcome
1501 | Li, Y.,Navia, J. M.,Caufield, P. W. (1994). Colonization by mutans streptococci in the mouths of 3- and 4-year-old Chinese children with or without enamel hypoplasia Arch Oral Biol, 39(12), 1057-62 | Study design
1502 | Liao, S. L.,Lai, S. H.,Yeh, K. W.,Huang, Y. L.,Yao, T. C.,Tsai, M. H.,Hua, M. C.,Huang, J. L. (2014). Exclusive breastfeeding is associated with reduced cow’s milk sensitization in early childhood Pediatr Allergy Immunol, 25(5), 456-61 | Outcome
1503 | Libraty, D. H.,Capeding, R. Z.,Obcena, A.,Brion, J. D.,Tallo, V. (2013). Breastfeeding During Early Infancy is Associated with a Lower Incidence of Febrile Illnesses Open Pediatr Med Journal, 7(#issue#), 40-41 | Country, Outcome
1504 | Liebrechts-Akkerman, G.,Lao, O.,Liu, F.,Van Sleuwen, B. E.,Engelberts, A. C.,L’Hoir, M. P.,Tiemeier, H. W.,Kayser, M. (2011). Postnatal parental smoking: An important risk factor for SIDS European Journal of Pediatrics, 170(10), 1281-1291 | Outcome
1505 | Lima, A. A.,Moore, S. R.,Barboza, M. S., Jr.,Soares, A. M.,Schleupner, M. A.,Newman, R. D.,Sears, C. L.,Nataro, J. P.,Fedorko, D. P.,Wuhib, T.,Schorling, J. B.,Guerrant, R. L. (2000). Persistent diarrhea signals a critical period of increased diarrhea burdens and nutritional shortfalls: a prospective cohort study among children in northeastern Brazil J Infect Dis, 181(5), 1643-51 | Outcome
1506 | Lin, H.,Sun, L.,Lin, J.,He, J.,Deng, A.,Kang, M.,Zeng, H.,Ma, W.,Zhang, Y. (2014). Protective effect of exclusive breastfeeding against hand, foot and mouth disease BMC Infect Dis, 14(#issue#), 645 | Study design, Outcome
1507 | Lind, J. N.,Li, R.,Perrine, C. G.,Schieve, L. A. (2014). Breastfeeding and later psychosocial development of children at 6 years of age Pediatrics, 134 Suppl 1(#issue#), S36-41 | Outcome
1508 | Lindberg, S. M.,Adams, A. K.,Prince, R. J. (2012). Early predictors of obesity and cardiovascular risk among American Indian children Matern Child Health J, 16(9), 1879-86 | Intervention/exposure
1509 | Lindenberg, C. S.,Artola, R. C.,Estrada, V. J. (1990). Determinants of early infant weaning: a multivariate approach Int J Nurs Stud, 27(1), 35-41 | Country
1510 | Lindfors, A. T.,Danielsson, L.,Enocksson, E.,Johansson, S. G.,Westin, S. (1992). Allergic symptoms up to 4-6 years of age in children given cow milk neonatally. A prospective study Allergy, 47(3), 207-11 | Intervention/exposure
1511 | Lindfors, A.,Enocksson, E. (1988). Development of atopic disease after early administration of cow milk formula Allergy, 43(1), 11-6 | Intervention/exposure
1512 | Linhares Rda, S.,Gigante, D. P.,de Barros, F. C.,Horta, B. L. (2015). Carotid intima-media thickness at age 30, birth weight, accelerated growth during infancy and breastfeeding: a birth cohort study in Southern Brazil PLoS One, 10(1), e0115166 | Intervention/exposure
1513 | Linhares, A. C.,Gabbay, Y. B.,Freitas, R. B.,da Rosa, E. S.,Mascarenhas, J. D.,Loureiro, E. C. (1989). Longitudinal study of rotavirus infections among children from Belem, Brazil Epidemiol Infect, 102(1), 129-45 | Outcome
1514 | Linneberg, A.,Simonsen, J. B.,Petersen, J.,Stensballe, L. G.,Benn, C. S. (2006). Differential effects of risk factors on infant wheeze and atopic dermatitis emphasize a different etiology J Allergy Clin Immunol, 117(1), 184-9 | Intervention/exposure
1515 | Lionetti, E.,Castellaneta, S.,Francavilla, R.,Pulvirenti, A.,Tonutti, E.,Amarri, S.,Barbato, M.,Barbera, C.,Barera, G.,Bellantoni, A.,Castellano, E.,Guariso, G.,Limongelli, M. G.,Pellegrino, S.,Polloni, C.,Ughi, C.,Zuin, G.,Fasano, A.,Catassi, C. (2014). Introduction of gluten, HLA status, and the risk of celiac disease in children N Engl J Med, 371(14), 1295-303 | Outcome
1516 | Lionetti, E.,Castellaneta, S.,Francavilla, R.,Pulvirenti, A.,Tonutti, E.,Amarri, S.,Barbato, M.,Barbera, C.,Barera, G.,Bellantoni, A.,Castellano, E.,Limongelli, M. G.,Pellegrino, S.,Polloni, C.,Ughi, C.,Zuin, G.,Guariso, G.,Fasano, A.,Catassi, C. (2014). Infant feeding pattern, HLA status, and prevalence of celiac disease Digestive and liver disease, 46(#issue#), e75-e76 | Publication status
1517 | Lionetti, E.,Castellaneta, S.,Pulvirenti, A.,Tonutti, E.,Francavilla, R.,Fasano, A.,Catassi, C. (2012). Prevalence and natural history of potential celiac disease in at-family-risk infants prospectively investigated from birth J Pediatr, 161(5), 908-14 | Size of study groups
1518 | Lipsman, S.,Dewey, K. G.,Lonnerdal, B. (1985). Breast-feeding among teenage mothers: milk composition, infant growth, and maternal dietary intake J Pediatr Gastroenterol Nutr, 4(3), 426-34 | Size of study groups
1519 | Litmanovitz, I.,Davidson, K.,Eliakim, A.,Regev, R. H.,Dolfin, T.,Arnon, S.,Bar-Yoseph, F.,Goren, A.,Lifshitz, Y.,Nemet, D. (2013). High Beta-palmitate formula and bone strength in term infants: a randomized, double-blind, controlled trial Calcif Tissue Int, 92(1), 35-41 | Study design, Size of study groups, Outcome
1520 | Little, R. E.,Lambert, M. D., 3rd,Worthington-Roberts, B.,Ervin, C. H. (1994). Maternal smoking during lactation: relation to infant size at one year of age Am J Epidemiol, 140(6), 544-54 | Outcome
1521 | Liu, J. (1990). Neglected problem: nursing bottle syndrome Dentistry (Loma Linda), 3(2), 57-8 | Study design
1522 | Liu, J.,Leung, P.,Yang, A. (2014). Breastfeeding and active bonding protects against children’s internalizing behavior problems Nutrients, 6(1), 76-89 | Study design, Intervention/exposure
1523 | Liu, Y. Q.,Qian, Z.,Wang, J.,Lu, T.,Lin, S.,Zeng, X. W.,Liu, R. Q.,Zhu, Y.,Qin, X. D.,Yuan, P.,Zhou, Y.,Li, M.,Hao, Y. T.,Dong, G. H. (2015). Breastfeeding modifies the effects of environment tobacco smoke exposure on respiratory diseases and symptoms in Chinese children: the Seven Northeast Cities Study Indoor Air, #volume#(#issue#), #Pages# | Study design
1524 | Livingstone, V. (2006). Failure to thrive while breastfeeding Breastfeed Med, 1(2), 108-11 | Study design
1525 | Livny, A.,Assali, R.,Sgan-Cohen, H. D. (2007). Early Childhood Caries among a Bedouin community residing in the eastern outskirts of Jerusalem BMC Public Health, 7(#issue#), 167 | Study design
1526 | Lnnerdal, B.,Timby, N.,Domellf, M.,Domellf, E.,Hernell, O. (2014). Supplementation of infant formula with milk fat globule membranes improves cognitive performance and reduces infections in formula-fed infants FASEB journal, 28(1 suppl. 1), #Pages# | Publication status
1527 | Lo, G. L. (1985). The use of comforters and dental caries in the Singaporean preschool children Singapore Dent J, 10(1), 21-4 | Intervention/exposure
1528 | Lodge, C. J.,Zaloumis, S.,Lowe, A. J.,Gurrin, L. C.,Matheson, M. C.,Axelrad, C.,Bennett, C. M.,Hill, D. J.,Hosking, C. S.,Svanes, C.,Abramson, M. J.,Allen, K. J.,Dharmage, S. C. (2014). Early-life risk factors for childhood wheeze phenotypes in a high-risk birth cohort J Pediatr, 164(2), 289-94 e1-2 | Outcome
1529 | Lodinova, R.,Jouja, V.,Vinsova, N.,Vocel, J.,Melkova, J. (1980). New attempts and possibilities in prevention and treatment of intestinal coli-infections in infants Czech Med, 3(1), 47-58 | Study design, Outcome
1530 | Lodinova-Zadnikova, R.,Tlaskalova, H.,Bartakova, Z. (1991). The antibody response in infants after colonization of the intestine with E. coli O83. Artificial colonization used as a prevention against nosocomial infections Adv Exp Med Biol, 310(#issue#), 329-35 | Study design, Size of study groups
1531 | Loeb H,Mozin MJ (1983). Prevention of chronic diarrhea: nutritional implications J Pediatr Gastroenterol Nutr, 2 Suppl 1(#issue#), S328-34 | Study design, Size of study groups
1532 | Long, K. Z.,Wood, J. W.,Vasquez Gariby, E.,Weiss, K. M.,Mathewson, J. J.,de la Cabada, F. J.,DuPont, H. L.,Wilson, R. A. (1994). Proportional hazards analysis of diarrhea due to enterotoxigenic Escherichia coli and breast feeding in a cohort of urban Mexican children Am J Epidemiol, 139(2), 193-205 | Outcome
1533 | Long, K.,Vasquez-Garibay, E.,Mathewson, J.,de la Cabada, J.,DuPont, H. (1999). The impact of infant feeding patterns on infection and diarrheal disease due to enterotoxigenic Escherichia coli Salud Publica Mex, 41(4), 263-70 | Intervention/exposure
1534 | Long, S. A.,Bugg, K. (2015). Can’t we all just get along? J Hum Lact, 31(1), 29-31 | Study design
1535 | Lonnerdal, B.,Havel, P. J. (2000). Serum leptin concentrations in infants: effects of diet, sex, and adiposity Am J Clin Nutr, 72(2), 484-9 | Intervention/exposure
1536 | Lonnerdal, B.,Hernell, O. (1994). Iron, zinc, copper and selenium status of breast-fed infants and infants fed trace element fortified milk-based infant formula Acta Paediatr, 83(4), 367-73 | Intervention/exposure
1537 | Lonnerdal, B.,Hernell, O. (1998). Effects of feeding ultrahigh-temperature (UHT)-treated infant formula with different protein concentrations or powdered formula, as compared with breast-feeding, on plasma amino acids, hematology, and trace element status Am J Clin Nutr, 68(2), 350-6 | Outcome
1538 | Lonnerdal, B.,Kvistgaard, A. S.,Peerson, J. M.,Donovan, S. M.,Peng, Y. M. (2015). Growth, Nutrition and Cytokine Response of Breast-Fed Infants and Infants Fed Formula with Added Bovine Osteopontin J Pediatr Gastroenterol Nutr, #volume#(#issue#), #Pages# | Intervention/exposure
1539 | Lopez Bravo, I. M.,Sepulveda, H.,Valdes, I. (1997). Acute respiratory illnesses in the first 18 months of life Rev Panam Salud Publica, 1(1), 9-17 | Outcome
1540 | Lopez Bravo, I.,Cabiol, C.,Arcuch, S.,Rivera, E.,Vargas, S. (1984). Breast-feeding, weight gains, diarrhea, and malnutrition in the first year of life Bull Pan Am Health Organ, 18(2), 151-63 | Outcome
1541 | Lopez Del Valle, L. M.,Singh, G. D.,Feliciano, N.,Machuca Mdel, C. (2006). Associations between a history of breast feeding, malocclusion and parafunctional habits in Puerto Rican children P R Health Sci J, 25(1), 31-4 | Study design
1542 | López, N.,De Barros-Mazón, S.,Dos Santos Vilela, M. M.,Silva, C. M.,Ribeiro, J. D. (1999). Genetic and environmental influences on atonic immune response in early life Journal of Investigational Allergology and Clinical Immunology, 9(6), 392-398 | Outcome
1543 | Lopez, N.,de Barros-Mazon, S.,Vilela, M. M.,Silva, C. M.,Ribeiro, J. D. (1999). Genetic and environmental influences on atopic immune response in early life J Investig Allergol Clin Immunol, 9(6), 392-8 | Outcome
1544 | Lopez-Alarcon, M.,Garcia-Zuniga, P.,Del Prado, M.,Garza, C. (2004). Breastfeeding protects against the anorectic response to infection in infants: possible role of DHA Adv Exp Med Biol, 554(#issue#), 371-4 | Size of study groups
1545 | Lopez-Alarcon, M.,Garza, C.,del Prado, M.,Garcia-Zuniga, P. A.,Barbosa, L. (2008). Breastfeeding’s protection against illness-induced anorexia is mediated partially by docosahexaenoic acid Eur J Clin Nutr, 62(1), 32-8 | Size of study groups
1546 | Lopez-Alarcon, M.,Villalpando, S.,Fajardo, A. (1997). Breast-feeding lowers the frequency and duration of acute respiratory infection and diarrhea in infants under six months of age J Nutr, 127(3), 436-43 | Outcome
1547 | Lopez-Lopez, A.,Castellote-Bargallo, A. I.,Campoy-Folgoso, C.,Rivero-Urgel, M.,Tormo-Carnice, R.,Infante-Pina, D.,Lopez-Sabater, M. C. (2001). The influence of dietary palmitic acid triacylglyceride position on the fatty acid, calcium and magnesium contents of at term newborn faeces Early Hum Dev, 65 Suppl(#issue#), S83-94 | Size of study groups
1548 | Losonsky, G. A.,D’Alessandra de Rimer, H. (1991). Rotavirus specific breast milk antibody in two populations and possible correlates of protection Adv Exp Med Biol, 310(#issue#), 265-9 | Study design, Outcome
1549 | Louzada, M. L.,Campagnolo, P. D.,Rauber, F.,Vitolo, M. R. (2012). Long-term effectiveness of maternal dietary counseling in a low-income population: a randomized field trial Pediatrics, 129(6), e1477-84 | Intervention/exposure
1550 | Lowe, A. J.,Carlin, J. B.,Bennett, C. M.,Abramson, M. J.,Hosking, C. S.,Hill, D. J.,Dharmage, S. C. (2006). Atopic disease and breast-feeding--cause or consequence? J Allergy Clin Immunol, 117(3), 682-7 | Intervention/exposure
1551 | Lozoff, B.,Wolf, A. W.,Jimenez, E. (1996). Iron-deficiency anemia and infant development: effects of extended oral iron therapy J Pediatr, 129(3), 382-9 | Study design
1552 | Lu, R.,Costello, A. (2000). Failure to exclusively breastfeed and the risk of early infant mortality due to infectious disease in poor communities in Lima, Peru J Trop Pediatr, 46(5), 309-11 | Outcome
1553 | Lubis, I. Z.,Sinuhaji, A. B.,Sebayang, T.,Lubis, M.,Barus, N.,Sutanto, A. H. (1985). Factors influencing the duration of infantile diarrhea Paediatr Indones, 25(9-10), 175-89 | Country
1554 | Lucas, A.,Boyes, S.,Bloom, S. R.,Aynsley-Green, A. (1981). Metabolic and endocrine responses to a milk feed in six-day-old term infants: differences between breast and cow’s milk formula feeding Acta Paediatr Scand, 70(2), 195-200 | Study design, Outcome
1555 | Lucas, A.,Ewing, G.,Roberts, S. B.,Coward, W. A. (1987). How much energy does the breast fed infant consume and expend? Br Med J (Clin Res Ed), 295(6590), 75-7 | Size of study groups
1556 | Lucas, A.,Lockton, S.,Davies, P. S. (1992). Randomised trial of a ready-to-feed compared with powdered formula Arch Dis Child, 67(7), 935-9 | Study design, Size of study groups
1557 | Lucas, A.,Stafford, M.,Morley, R.,Abbott, R.,Stephenson, T.,MacFadyen, U.,Elias-Jones, A.,Clements, H. (1999). Efficacy and safety of long-chain polyunsaturated fatty acid supplementation of infant-formula milk: a randomised trial Lancet, 354(9194), 1948-54 | Outcome
1558 | Lucas, Ruth F. (2011). Maternal Breastfeeding Experiences and Neonatal Breastfeeding Behaviors of Children Later Diagnosed with Autism #journal#, Ph.D.(#issue#), 152 p-152 p 1p | Publication status
1559 | Luccioli, S.,Zhang, Y.,Verrill, L.,Ramos-Valle, M.,Kwegyir-Afful, E. (2014). Infant feeding practices and reported food allergies at 6 years of age Pediatrics, 134 Suppl 1(#issue#), S21-8 | Intervention/exposure
1560 | Ludvigsson, J. (2003). Cow-milk-free diet during last trimester of pregnancy does not influence diabetes-related autoantibodies in nondiabetic children Ann N Y Acad Sci, 1005(#issue#), 275-8 | Outcome
1561 | Ludvigsson, J. F.,Mostrom, M.,Ludvigsson, J.,Duchen, K. (2005). Exclusive breastfeeding and risk of atopic dermatitis in some 8300 infants Pediatr Allergy Immunol, 16(3), 201-8 | Study design
1562 | Lulic-Dukic, O.,Juric, H.,Dukic, W.,Glavina, D. (2001). Factors predisposing to early childhood caries (ECC) in children of pre-school age in the city of Zagreb, Croatia Coll Antropol, 25(1), 297-302 | Study design
1563 | Lumia, M.,Takkinen, H. M.,Luukkainen, P.,Kaila, M.,Lehtinen-Jacks, S.,Nwaru, B. I.,Tuokkola, J.,Niemela, O.,Haapala, A. M.,Ilonen, J.,Simell, O.,Knip, M.,Veijola, R.,Virtanen, S. M. (2015). Food consumption and risk of childhood asthma Pediatr Allergy Immunol, #volume#(#issue#), #Pages# | Intervention/exposure
1564 | Lunardelli, S. E.,Peres, M. A. (2006). Breast-feeding and other mother-child factors associated with developmental enamel defects in the primary teeth of Brazilian children J Dent Child (Chic), 73(2), 70-8 | Outcome
1565 | Lundberg, G. D. (2008). Does breast-feeding improve child cognitive development? MedGenMed Medscape General Medicine, 10(8), #Pages# | Study design
1566 | Lund-Blix, N. A.,Stene, L. C.,Rasmussen, T.,Torjesen, P. A.,Andersen, L. F.,Ronningen, K. S. (2015). Infant feeding in relation to islet autoimmunity and type 1 diabetes in genetically susceptible children: the MIDIA Study Diabetes Care, 38(2), 257-63 | Outcome
1567 | Lundqvist-Persson, C. (2001). Correlation between level of self-regulation in the newborn infant and developmental status at two years of age Acta Paediatrica, International Journal of Paediatrics, 90(3), 345-350 | Size of study groups
1568 | Lung, F. W.,Chiang, T. L.,Lin, S. J.,Shu, B. C. (2013). Incinerator pollution and child development in the taiwan birth cohort study Int J Environ Res Public Health, 10(6), 2241-57 | Intervention/exposure
1569 | Luo, R.,Shi, Y.,Zhou, H.,Yue, A.,Zhang, L.,Sylvia, S.,Medina, A.,Rozelle, S. (2014). Anemia and feeding practices among infants in rural Shaanxi Province in China Nutrients, 6(12), 5975-91 | Study design
1570 | Luo,,R,,Shi,,Y,,Zhou,,H,,Yue,,A,,Zhang,,L,,Sylvia,,S,,Medina,,A,,Rozelle,,S, (2014). Anemia and feeding practices among infants in rural Shaanxi Province in China Nutrients, 6(12), 5975-91 | Study design
1571 | Luoma, R. (1984). Environmental allergens and morbidity in atopic and non-atopic families Acta Paediatr Scand, 73(4), 448-53 | Outcome
1572 | Luopajarvi, K.,Savilahti, E.,Virtanen, S. M.,Ilonen, J.,Knip, M.,Akerblom, H. K.,Vaarala, O. (2008). Enhanced levels of cow’s milk antibodies in infancy in children who develop type 1 diabetes later in childhood Pediatr Diabetes, 9(5), 434-41 | Size of study groups
1573 | Lutter, C. K. (2000). Breastfeeding promotion--is its effectiveness supported by scientific evidence and global changes in breastfeeding behaviors? Adv Exp Med Biol, 478(#issue#), 355-68 | Publication status
1574 | Lyall, J. (1991). Growing problems Nurs Times, 87(24), 22-3 | Study design
1575 | Ma, D. Q.,Jones, G. (2002). Clinical risk factors but not bone density are associated with prevalent fractures in prepubertal children J Paediatr Child Health, 38(5), 497-500 | Study design
1576 | Ma, J. Q.,Zhou, L. L.,Hu, Y. Q.,Liu, J. R.,Liu, S. S.,Zhang, J.,Sheng, X. Y. (2012). A summary index of infant and child feeding practices is associated with child growth in urban Shanghai BMC Public Health, 12(#issue#), 568 | Intervention/exposure
1577 | Maas, T.,Dompeling, E.,Muris, J. W.,Wesseling, G.,Knottnerus, J. A.,van Schayck, O. C. (2011). Prevention of asthma in genetically susceptible children: a multifaceted intervention trial focussed on feasibility in general practice Pediatr Allergy Immunol, 22(8), 794-802 | Outcome
1578 | MacArthur, A. C.,McBride, M. L.,Spinelli, J. J.,Tamaro, S.,Gallagher, R. P.,Theriault, G. P. (2008). Risk of childhood leukemia associated with vaccination, infection, and medication use in childhood: the Cross-Canada Childhood Leukemia Study Am J Epidemiol, 167(5), 598-606 | Outcome
1579 | MacDonald, L. D.,Gibson, R. S.,Miles, J. E. (1982). Changes in hair zinc and copper concentrations of breast fed and bottle fed infants during the first six months Acta Paediatr Scand, 71(5), 785-9 | Size of study groups
1580 | Macdonald, P. D.,Ross, S. R.,Grant, L.,Young, D. (2003). Neonatal weight loss in breast and formula fed infants Arch Dis Child Fetal Neonatal Ed, 88(6), F472-6 | Outcome
1581 | MacIntyre, E. A.,Karr, C. J.,Koehoorn, M.,Demers, P.,Tamburic, L.,Lencar, C.,Brauer, M. (2010). Otitis media incidence and risk factors in a population-based birth cohort Paediatrics and Child Health, 15(7), 437-442 | Outcome
1582 | Macoun, E. (2005). The NSW Health Breastfeeding Project N S W Public Health Bull, 16(3-4), 62 | Study design
1583 | Madar, A. A.,Stene, L. C.,Meyer, H. E. (2009). Vitamin D status among immigrant mothers from Pakistan, Turkey and Somalia and their infants attending child health clinics in Norway Br J Nutr, 101(7), 1052-8 | Study design
1584 | Madhavapeddi, R.,Ramachandran, P. (1990). Growth and morbidity of breastfed infants whose mothers were using combination pills Breastfeeding Review, 2(2), 66-68 3p | Country
1585 | Madhavapeddi, R.,Ramachandran, P. (1993). Growth of urban breastfed infants from low socio-economic group J Trop Pediatr, 39(6), 328-31 | Country
1586 | Madsen, A. L.,Larnkjaer, A.,Molgaard, C.,Michaelsen, K. F. (2011). IGF-I and IGFBP-3 in healthy 9 month old infants from the SKOT cohort: breastfeeding, diet, and later obesity Growth Horm IGF Res, 21(4), 199-204 | Study design, Intervention/exposure
1587 | Magalhaes, T. C.,Vieira, S. A.,Priore, S. E.,Ribeiro, A. Q.,Lamounier, J. A.,Franceschini, S. C.,Sant’Ana, L. F. (2012). Exclusive breastfeeding and other foods in the first six months of life: effects on nutritional status and body composition of Brazilian children ScientificWorldJournal, 2012(#issue#), 468581 | Intervention/exposure
1588 | Magana Cardenas, A.,Padilla Gonzalez, L. M.,Garcia de Alba, J. E.,Troyo San Roman, R.,Delgado Becerra, A. (1981). Some epidemiological aspects of maternal breast-feeding in a population entitled to social welfare services in Mexico Bull Pan Am Health Organ, 15(2), 139-47 | Outcome
1589 | Magnus, M. C.,DeRoo, L. A.,Haberg, S. E.,Magnus, P.,Nafstad, P.,Nystad, W.,London, S. J. (2014). Prospective study of maternal alcohol intake during pregnancy or lactation and risk of childhood asthma: the Norwegian Mother and Child Cohort Study Alcohol Clin Exp Res, 38(4), 1002-11 | Intervention/exposure
1590 | Magnusson, C. G. (1988). Cord serum IgE in relation to family history and as predictor of atopic disease in early infancy Allergy, 43(4), 241-51 | Study design, Outcome
1591 | Mai, X. M.,Becker, A. B.,Sellers, E. A.,Liem, J. J.,Kozyrskyj, A. L. (2007). The relationship of breast-feeding, overweight, and asthma in preadolescents J Allergy Clin Immunol, 120(3), 551-6 | Intervention/exposure
1592 | Maisels, M. J.,Gifford, K. (1983). Breast-feeding, weight loss, and jaundice J Pediatr, 102(1), 117-8 | Size of study groups, Intervention/exposure
1593 | Majeed, R.,Rajar, U. D.,Shaikh, N.,Majeed, F.,Arain, A. A. (2008). Risk factors associated with childhood asthma J Coll Physicians Surg Pak, 18(5), 299-302 | Country
1594 | Majorana, A.,Cagetti, M. G.,Bardellini, E.,Amadori, F.,Conti, G.,Strohmenger, L.,Campus, G. (2014). Feeding and smoking habits as cumulative risk factors for early childhood caries in toddlers, after adjustment for several behavioral determinants: a retrospective study BMC Pediatr, 14(#issue#), 45 | Outcome
1595 | Makela, J.,Linderborg, K.,Niinikoski, H.,Yang, B.,Lagstrom, H. (2013). Breast milk fatty acid composition differs between overweight and normal weight women: the STEPS Study Eur J Nutr, 52(2), 727-35 | Intervention/exposure, Outcome
1596 | Mäkelä, J.,Vaarno, J.,Kaljonen, A.,Niinikoski, H.,Lagström, H. (2014). Maternal overweight impacts infant feeding patterns - The STEPS Study European Journal of Clinical Nutrition, 68(1), 43-49 | Duplicate
1597 | Makela, J.,Vaarno, J.,Kaljonen, A.,Niinikoski, H.,Lagstrom, H. (2014). Maternal overweight impacts infant feeding patterns--the STEPS Study Eur J Clin Nutr, 68(1), 43-9 | Outcome
1598 | Maki, M.,Kallonen, K.,Lahdeaho, M. L.,Visakorpi, J. K. (1988). Changing pattern of childhood coeliac disease in Finland Acta Paediatr Scand, 77(3), 408-12 | Study design
1599 | Makrides M,Neumann MA,Byard RW,Simmer K,Gibson RA (1994). Fatty acid composition of brain, retina, and erythrocytes in breast- and formula-fed infants Am J Clin Nutr, 60(#issue#), 189-94 | Participant health
1600 | Makrides, M. (2008). Outcomes for mothers and their babies: do n-3 long-chain polyunsaturated fatty acids and seafoods make a difference? J Am Diet Assoc, 108(10), 1622-6 | Study design
1601 | Makrides, M.,Gibson, R. A.,Simmer, K. (1993). The effect of dietary fat on the developing brain J Paediatr Child Health, 29(6), 409-10 | Study design
1602 | Makrides, M.,Hawkes, J. S.,Neumann, M. A.,Gibson, R. A. (2002). Nutritional effect of including egg yolk in the weaning diet of breast-fed and formula-fed infants: a randomized controlled trial Am J Clin Nutr, 75(6), 1084-92 | Intervention/exposure
1603 | Makrides, M.,Neumann, M. A.,Simmer, K.,Gibson, R. A. (1995). Erythrocyte fatty acids of term infants fed either breast milk, standard formula, or formula supplemented with long-chain polyunsaturates Lipids, 30(10), 941-8 | Size of study groups
1604 | Makrides, M.,Neumann, M. A.,Simmer, K.,Gibson, R. A. (2000). A critical appraisal of the role of dietary long-chain polyunsaturated fatty acids on neural indices of term infants: a randomized, controlled trial Pediatrics, 105(1 Pt 1), 32-8 | Outcome
1605 | Makrides, M.,Neumann, M.,Gibson, R. (1997). Breast milk docosahexaenoic acid (DHA) and infant outcomes: a randomised clinical trial Journal of paediatrics and child health, 33(4), A2 | Publication status
1606 | Makrides, M.,Simmer, K.,Goggin, M.,Gibson, R. A. (1993). Erythrocyte docosahexaenoic acid correlates with the visual response of healthy, term infants Pediatr Res, 33(4 Pt 1), 425-7 | Study design, Size of study groups
1607 | Malcolm, C. A.,McCulloch, D. L.,Montgomery, C.,Shepherd, A.,Weaver, L. T. (2003). Maternal docosahexaenoic acid supplementation during pregnancy and visual evoked potential development in term infants: a double blind, prospective, randomised trial Arch Dis Child Fetal Neonatal Ed, 88(5), F383-90 | Intervention/exposure
1608 | Malcova, H.,Sumnik, Z.,Drevinek, P.,Venhacova, J.,Lebl, J.,Cinek, O. (2006). Absence of breast-feeding is associated with the risk of type 1 diabetes: a case-control study in a population with rapidly increasing incidence Eur J Pediatr, 165(2), 114-9 | Outcome
1609 | Malek L,Makrides M (2015). 2.8 Nutrition in pregnancy and lactation World Rev Nutr Diet, 113(#issue#), 127-33 | Publication status
1610 | Malinowska E,Kaczmarski M,Wasilewska J (2002). Total IgE levels and skin test results in children under three years of age with food hypersensitivity Med Sci Monit, 8(#issue#), Cr280-7 | Study design, Intervention/exposure
1611 | Mallet, E.,Henocq, A. (1992). Long-term prevention of allergic diseases by using protein hydrolysate formula in at-risk infants J Pediatr, 121(5 Pt 2), S95-100 | Outcome
1612 | Mallol-Mesnard, N.,Menegaux, F.,Lacour, B.,Hartmann, O.,Frappaz, D.,Doz, F.,Bertozzi, A. I.,Chastagner, P.,Hemon, D.,Clavel, J. (2008). Birth characteristics and childhood malignant central nervous sytem tumors: the ESCALE study (French Society for Childhood Cancer) Cancer Detect Prev, 32(1), 79-86 | Outcome
1613 | Malloy, M. H.,Berendes, H. (1998). Does breast-feeding influence intelligence quotients at 9 and 10 years of age? Early Hum Dev, 50(2), 209-17 | Study design, Intervention/exposure
1614 | Manco, M.,Alterio, A.,Bugianesi, E.,Ciampalini, P.,Mariani, P.,Finocchi, M.,Agostoni, C.,Nobili, V. (2011). Insulin dynamics of breast- or formula-fed overweight and obese children Journal of the American College of Nutrition, 30(1), 29-38 | Study design
1615 | Mandel, E. M.,Doyle, W. J.,Winther, B.,Alper, C. M. (2008). The incidence, prevalence and burden of OM in unselected children aged 1-8 years followed by weekly otoscopy through the “common cold” season Int J Pediatr Otorhinolaryngol, 72(4), 491-9 | Outcome
1616 | Mandhane, P. J.,Greene, J. M.,Sears, M. R. (2007). Interactions between breast-feeding, specific parental atopy, and sex on development of asthma and atopy J Allergy Clin Immunol, 119(6), 1359-66 | Intervention/exposure
1617 | Mandic, Z.,Piricki, A. P.,Kenjeric, D.,Hanicar, B.,Tanasic, I. (2011). Breast vs. bottle: differences in the growth of Croatian infants Matern Child Nutr, 7(4), 389-96 | Intervention/exposure
1618 | Mangskau, K. (1991). Baby bottle tooth decay: a problem affecting young children in North Dakota Northwest Dent, 70(6), 25 | Study design
1619 | Manjrekar, C.,Vishalakshi, M. P.,Begum, N. J.,Padma, G. N. (1985). Breast feeding ability of undernourished mothers and physical development of their infants during 0-1 year Indian Pediatr, 22(11), 801-9 | Country
1620 | Mann, K. D.,Tennant, P. W.,Parker, L.,Unwin, N. C.,Pearce, M. S. (2011). The relatively small contribution of birth weight to blood pressure at age 49-51 years in the Newcastle Thousand Families Study J Hypertens, 29(6), 1077-84 | Outcome
1621 | Maranhao, H. S.,Medeiros, M. C.,Scaletsky, I. C.,Fagundes-Neto, U.,Morais, M. B. (2008). The epidemiological and clinical characteristics and nutritional development of infants with acute diarrhoea, in north-eastern Brazil Ann Trop Med Parasitol, 102(4), 357-65 | Intervention/exposure
1622 | Marini, A.,Agosti, M.,Motta, G.,Mosca, F. (1996). Effects of a dietary and environmental prevention programme on the incidence of allergic symptoms in high atopic risk infants: three years’ follow-up Acta Paediatr Suppl, 414(#issue#), 1-21 | Intervention/exposure
1623 | Markestad, T. (1983). Effect of season and vitamin D supplementation on plasma concentrations of 25-hydroxyvitamin D in Norwegian infants Acta Paediatr Scand, 72(6), 817-21 | Study design, Intervention/exposure
1624 | Markestad, T. (1983). Plasma concentrations of 1,25-dihydroxyvitamin D, 24,25-dihydroxyvitamin D, and 25,26-dihydroxyvitamin D in the first year of life J Clin Endocrinol Metab, 57(4), 755-9 | Study design
1625 | Marmot, M. G.,Page, C. M.,Atkins, E.,Douglas, J. W. (1980). Effect of breast-feeding on plasma cholesterol and weight in young adults J Epidemiol Community Health, 34(3), 164-7 | Intervention/exposure
1626 | Marques, R. C.,Dorea, J. G.,Bernardi, J. V.,Bastos, W. R.,Malm, O. (2008). Maternal fish consumption in the nutrition transition of the Amazon Basin: growth of exclusively breastfed infants during the first 5 years Ann Hum Biol, 35(4), 363-77 | Outcome
1627 | Marques, R. C.,Dorea, J. G.,Bernardi, J. V.,Bastos, W. R.,Malm, O. (2009). Prenatal and postnatal mercury exposure, breastfeeding and neurodevelopment during the first 5 years Cogn Behav Neurol, 22(2), 134-41 | Intervention/exposure
1628 | Marques, R. C.,Dorea, J. G.,Leao, R. S.,Dos Santos, V. G.,Bueno, L.,Marques, R. C.,Brandao, K. G.,Palermo, E. F.,Guimaraes, J. R. (2012). Role of methylmercury exposure (from fish consumption) on growth and neurodevelopment of children under 5 years of age living in a transitioning (tin-mining) area of the western Amazon, Brazil Arch Environ Contam Toxicol, 62(2), 341-50 | Study design, Intervention/exposure
1629 | Marques, R. F.,Taddei, J. A.,Lopez, F. A.,Braga, J. A. (2014). Breastfeeding exclusively and iron deficiency anemia during the first 6 months of age Rev Assoc Med Bras, 60(1), 18-22 | Intervention/exposure
1630 | Marquis, G. S.,Habicht, J. P. (2000). Breastfeeding and stunting among toddlers in Peru Adv Exp Med Biol, 478(#issue#), 163-72 | Publication status
1631 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. (1997). Association of breastfeeding and stunting in Peruvian toddlers: an example of reverse causality Int J Epidemiol, 26(2), 349-56 | Intervention/exposure
1632 | Marquis, G. S.,Habicht, J. P.,Lanata, C. F.,Black, R. E.,Rasmussen, K. M. (1997). Breast milk or animal-product foods improve linear growth of Peruvian toddlers consuming marginal diets Am J Clin Nutr, 66(5), 1102-9 | Intervention/exposure
1633 | Marriage, B. J.,Buck, R. H.,Goehring, K. C.,Oliver, J. S.,Williams, J. A. (2015). Infants Fed a Lower Calorie Formula With 2’FL Show Growth and 2’FL Uptake Like Breast-Fed Infants J Pediatr Gastroenterol Nutr, 61(6), 649-58 | Outcome
1634 | Marshall, J. (2013). Infant feeding. 6. Formula feed Pract Midwife, 16(3), 35-8 | Study design
1635 | Martel, M. J.,Rey, E.,Malo, J. L.,Perreault, S.,Beauchesne, M. F.,Forget, A.,Blais, L. (2009). Determinants of the incidence of childhood asthma: a two-stage case-control study Am J Epidemiol, 169(2), 195-205 | Outcome
1636 | Martens, P. J.,Romphf, L. (2007). Factors associated with newborn in-hospital weight loss: comparisons by feeding method, demographics, and birthing procedures J Hum Lact, 23(3), 233-41, quiz 242-5 | Outcome
1637 | Martin FP,Moco S,Montoliu I,Collino S,Da Silva L,Rezzi S,Prieto R,Kussmann M,Inostroza J,Steenhout P (2014). Impact of breast-feeding and high- and low-protein formula on the metabolism and growth of infants from overweight and obese mothers Pediatr Res, 75(#issue#), 535-43 | Outcome
1638 | Martin, A. J.,Landau, L. I.,Phelan, P. D. (1981). Natural history of allergy in asthmatic children followed to adult life Med J Aust, 2(9), 470-4 | Study design, Intervention/exposure
1639 | Martin, R. M.,Ben-Shlomo, Y.,Gunnell, D.,Elwood, P.,Yarnell, J. W.,Davey Smith, G. (2005). Breast feeding and cardiovascular disease risk factors, incidence, and mortality: the Caerphilly study J Epidemiol Community Health, 59(2), 121-9 | Study design
1640 | Martin, R. M.,Ebrahim, S.,Griffin, M.,Davey Smith, G.,Nicolaides, A. N.,Georgiou, N.,Watson, S.,Frankel, S.,Holly, J. M.,Gunnell, D. (2005). Breastfeeding and atherosclerosis: intima-media thickness and plaques at 65-year follow-up of the Boyd Orr cohort Arterioscler Thromb Vasc Biol, 25(7), 1482-8 | Intervention/exposure
1641 | Martin, R. M.,Gunnell, D.,Pemberton, J.,Frankel, S.,Smith, G. D. (2005). Cohort profile: The Boyd Orr cohort - An historical cohort study based on the 65 year follow-up of the Carnegie Survey of Diet and Health (1937-39) International Journal of Epidemiology, 34(4), 742-749 | Study design
1642 | Martin, R. M.,Ness, A. R.,Gunnell, D.,Emmett, P.,Davey Smith, G. (2004). Does breast-feeding in infancy lower blood pressure in childhood? The Avon Longitudinal Study of Parents and Children (ALSPAC) Circulation, 109(10), 1259-66 | Outcome
1643 | Martin, R. M.,Patel, R.,Kramer, M. S.,Guthrie, L.,Vilchuck, K.,Bogdanovich, N.,Sergeichick, N.,Gusina, N.,Foo, Y.,Palmer, T.,Rifas-Shiman, S. L.,Gillman, M. W.,Smith, G. D.,Oken, E. (2013). Effects of promoting longer-term and exclusive breastfeeding on adiposity and insulin-like growth factor-I at age 11.5 years: a randomized trial JAMA, 309(10), 1005-13 | Outcome
1644 | Martin, R. M.,Patel, R.,Kramer, M. S.,Vilchuck, K.,Bogdanovich, N.,Sergeichick, N.,Gusina, N.,Foo, Y.,Palmer, T.,Thompson, J.,Gillman, M. W.,Smith, G. D.,Oken, E. (2014). Effects of promoting longer-term and exclusive breastfeeding on cardiometabolic risk factors at age 11.5 years: a cluster-randomized, controlled trial Circulation, 129(3), 321-9 | Outcome
1645 | Martin, R. M.,Smith, G. D.,Mangtani, P.,Frankel, S.,Gunnell, D. (2002). Association between breast feeding and growth: the Boyd-Orr cohort study Arch Dis Child Fetal Neonatal Ed, 87(3), F193-201 | Study design, Intervention/exposure
1646 | Martines, F.,Bentivegna, D.,Maira, E.,Sciacca, V.,Martines, E. (2011). Risk factors for otitis media with effusion: case-control study in Sicilian schoolchildren Int J Pediatr Otorhinolaryngol, 75(6), 754-9 | Study design
1647 | Martines, F.,Salvago, P.,Ferrara, S.,Messina, G.,Mucia, M.,Plescia, F.,Sireci, F. (2015). Factors influencing the development of otitis media among Sicilian children affected by upper respiratory tract infections Brazilian Journal of Otorhinolaryngology, #volume#(#issue#), #Pages# | Outcome
1648 | Martines, J. C.,Ashworth, A.,Kirkwood, B. (1989). Breast-feeding among the urban poor in southern Brazil: reasons for termination in the first 6 months of life Bull World Health Organ, 67(2), 151-61 | Outcome
1649 | Martines, J. C.,Habicht, J. P.,Ashworth, A.,Kirkwood, B. R. (1994). Weaning in southern Brazil: is there a “weanling’s dilemma”? J Nutr, 124(8), 1189-98 | Intervention/exposure
1650 | Martorell, A.,Plaza, A. M.,Boné, J.,Nevot, S.,García Ara Ma, C.,Echeverria, L.,Alonso, E.,Garde, J.,Vila, B.,Alvaro, M.,Tauler, E.,Hernando, V.,Fernández, M. (2006). Cow’s milk protein allergy. A multi-centre study: Clinical and epidemiological aspects Allergologia et Immunopathologia, 34(2), 46-53 | Study design, Intervention/exposure
1651 | Martorell, R.,O’Gara, C. (1985). Breastfeeding, infant health, and socioeconomic status Med Anthropol, 9(2), 173-81 | Country
1652 | Mason, J. K.,Harkness, R. A.,Elton, R. A.,Bartholomew, S. (1980). Cot deaths in Edinburgh: infant feeding and socioeconomic factors J Epidemiol Community Health, 34(1), 35-41 | Study design, Intervention/exposure
1653 | Massoni, A. C.,Chaves, A. M.,Rosenblatt, A.,Sampaio, F. C.,Oliveira, A. F. (2009). Prevalence of enamel defects related to pre-, peri- and postnatal factors in a Brazilian population Community Dent Health, 26(3), 143-9 | Study design
1654 | Mata, L. (1981). Epidemiologic perspective of diarrheal disease in Costa Rica and current efforts in control, prevention, and research Rev Latinoam Microbiol, 23(2), 109-19 | Study design
1655 | Mata, L. (1986). Cryptosporidium and other protozoa in diarrheal disease in less developed countries Pediatr Infect Dis, 5(1 Suppl), S117-30 | Study design
1656 | Mata, L.,Bolanos, H.,Pizarro, D.,Vives, M. (1984). Cryptosporidiosis in children from some highland Costa Rican rural and urban areas Am J Trop Med Hyg, 33(1), 24-9 | Study design, Intervention/exposure
1657 | Matee MI,Mikx FH,Maselle SY,Van Palenstein Helderman WH (1992). Rampant caries and linear hypoplasia (short communication) Caries Res, 26(#issue#), 205-8 | Country
1658 | Matheson, M. C.,Erbas, B.,Balasuriya, A.,Jenkins, M. A.,Wharton, C. L.,Tang, M. L.,Abramson, M. J.,Walters, E. H.,Hopper, J. L.,Dharmage, S. C. (2007). Breast-feeding and atopic disease: a cohort study from childhood to middle age J Allergy Clin Immunol, 120(5), 1051-7 | Intervention/exposure
1659 | Matsuda, I.,Higashi, A.,Ikeda, T.,Uehara, I.,Kuroki, Y. (1984). Effects of zinc and copper content of formulas on growth and on the concentration of zinc and copper in serum and hair J Pediatr Gastroenterol Nutr, 3(3), 421-5 | Study design, Size of study groups
1660 | Matthews, M. K.,Webber, K.,McKim, E.,Banoub-Baddour, S.,Laryea, M. (1995). Infant feeding practices in Newfoundland and Labrador Can J Public Health, 86(5), 296-300 | Outcome
1661 | Mattos-Graner, R. O.,Zelante, F.,Line, R. C.,Mayer, M. P. (1998). Association between caries prevalence and clinical, microbiological and dietary variables in 1.0 to 2.5-year-old Brazilian children Caries Res, 32(5), 319-23 | Study design
1662 | Maupome, G.,Karanja, N.,Ritenbaugh, C.,Lutz, T.,Aickin, M.,Becker, T. (2010). Dental caries in American Indian toddlers after a community-based beverage intervention Ethn Dis, 20(4), 444-50 | Intervention/exposure
1663 | May, R.,Barber, J.,Simpson, T.,Winders, N.,Kuhler, K.,Schroeder, S. (2002). Growth pattern of overweight preschool children in the Siouxland WIC program Am J Hum Biol, 14(6), 769-76 | Participant health
1664 | May, R.,Kim, D.,Mote-Watson, D. (2013). Change in weight-for-length status during the first three months: relationships to birth weight and implications for metabolic risk Am J Phys Anthropol, 150(1), 5-9 | Study design
1665 | Mayer, E. J.,Hamman, R. F.,Gay, E. C.,Lezotte, D. C.,Savitz, D. A.,Klingensmith, G. J. (1988). Reduced risk of IDDM among breast-fed children. The Colorado IDDM Registry Diabetes, 37(12), 1625-32 | Outcome
1666 | Mayer-Davis, E. J.,Dabelea, D.,Crandell, J. L.,Crume, T.,D’Agostino, R. B., Jr.,Dolan, L.,King, I. B.,Lawrence, J. M.,Norris, J. M.,Pihoker, C.,The, N. (2013). Nutritional factors and preservation of C-peptide in youth with recently diagnosed type 1 diabetes: SEARCH Nutrition Ancillary Study Diabetes Care, 36(7), 1842-50 | Study design, Outcome, Participant health
1667 | Mayer-Davis, E. J.,Dabelea, D.,Lamichhane, A. P.,D’Agostino Jr, R. B.,Liese, A. D.,Thomas, J.,McKeown, R. E.,Hamman, R. F. (2008). Breast-feeding and type 2 diabetes in the youth of three ethnic groups: The SEARCH for diabetes in youth case-control study Diabetes Care, 31(3), 470-475 | Outcome
1668 | Mayer-Davis, E. J.,Rifas-Shiman, S. L.,Zhou, L.,Hu, F. B.,Colditz, G. A.,Gillman, M. W. (2006). Breast-feeding and risk for childhood obesity: does maternal diabetes or obesity status matter? Diabetes Care, 29(10), 2231-7 | Study design
1669 | McAllister, J. C.,Lane, A. T.,Buckingham, B. A. (2006). Vitamin D deficiency in the San Francisco Bay Area J Pediatr Endocrinol Metab, 19(3), 205-8 | Study design
1670 | McCann, M. F.,Moggia, A. V.,Higgins, J. E.,Potts, M.,Becker, C. (1989). The effects of a progestin-only oral contraceptive (levonorgestrel 0.03 mg) on breast-feeding Contraception, 40(6), 635-48 | Intervention/exposure
1671 | McConnochie, K. M.,Roghmann, K. J. (1986). Breast feeding and maternal smoking as predictors of wheezing in children age 6 to 10 years Pediatr Pulmonol, 2(5), 260-8 | Intervention/exposure
1672 | McCormick, D. P.,Grady, J. J.,Diego, A.,Matalon, R.,Revai, K.,Patel, J. A.,Han, Y.,Chonmaitree, T. (2011). Acute otitis media severity: association with cytokine gene polymorphisms and other risk factors Int J Pediatr Otorhinolaryngol, 75(5), 708-12 | Outcome
1673 | McCrory, C.,Layte, R. (2012). Breastfeeding and risk of overweight and obesity at nine-years of age Soc Sci Med, 75(2), 323-30 | Study design
1674 | McCrory, C.,Murray, A. (2013). The effect of breastfeeding on neuro-development in infancy Matern Child Health J, 17(9), 1680-8 | Study design
1675 | McCusker, C. (2008). Teaching tolerance: Using the neonatal immune system to prevent allergic asthma Expert Review of Clinical Immunology, 4(4), 429-432 | Study design
1676 | McDougall, P.,Drewett, R. F.,Hungin, A. P. S.,Wright, C. M. (2009). The detection of early weight faltering at the 6-8-week check and its association with family factors, feeding and behavioural development Archives of Disease in Childhood, 94(7), 549-552 | Outcome
1677 | McEnery, G.,Rao, K. P. (1986). The effectiveness of antenatal education of Pakistani and Indian women living in this country Child Care Health Dev, 12(6), 385-99 | Intervention/exposure
1678 | McGowan, E. C.,Bloomberg, G. R.,Gergen, P. J.,Visness, C. M.,Jaffee, K. F.,Sandel, M.,O’Connor, G.,Kattan, M.,Gern, J.,Wood, R. A. (2015). Influence of early-life exposures on food sensitization and food allergy in an inner-city birth cohort J Allergy Clin Immunol, 135(1), 171-8 | Outcome
1679 | McIntosh, E. D.,De Silva, L. M.,Oates, R. K. (1993). Clinical severity of respiratory syncytial virus group A and B infection in Sydney, Australia Pediatr Infect Dis J, 12(10), 815-9 | Participant health
1680 | McIsaac, K. E.,Moineddin, R.,Matheson, F. I. (2015). Breastfeeding as a means to prevent infant morbidity and mortality in Aboriginal Canadians: A population prevented fraction analysis Can J Public Health, 106(4), e217-22 | Study design
1681 | McKinney, P. A.,Parslow, R.,Gurney, K. A.,Law, G. R.,Bodansky, H. J.,Williams, R. (1999). Perinatal and neonatal determinants of childhood type 1 diabetes. A case-control study in Yorkshire, U.K Diabetes Care, 22(6), 928-32 | Intervention/exposure
1682 | McMichael, A. J. (2005). Widening the horizons of ‘evidence’: Nutrition and disease in ecological perspective South African Journal of Clinical Nutrition, 18(2), 140-148 | Study design
1683 | McNamara, T. M.,Melnyk, B. M. (2000). The effect of food intake on atopic disease in high-risk infants and young children Pediatric nursing, 26(6), 602-604 | Study design
1684 | McTeer, H. (2012). Fat, young, and poor: why breastfeeding is a critical weapon in the fight against childhood obesity Breastfeed Med, 7(5), 325-6 | Study design
1685 | Meador, K. J.,Baker, G. A.,Browning, N.,Clayton-Smith, J.,Combs-Cantrell, D. T.,Cohen, M.,Kalayjian, L. A.,Kanner, A.,Liporace, J. D.,Pennell, P. B.,Privitera, M.,Loring, D. W. (2010). Effects of breastfeeding in children of women taking antiepileptic drugs Neurology, 75(22), 1954-60 | Intervention/exposure
1686 | Meador, K. J.,Baker, G. A.,Browning, N.,Cohen, M. J.,Bromley, R. L.,Clayton-Smith, J.,Kalayjian, L. A.,Kanner, A.,Liporace, J. D.,Pennell, P. B.,Privitera, M.,Loring, D. W. (2014). Breastfeeding in children of women taking antiepileptic drugs: cognitive outcomes at age 6 years JAMA Pediatr, 168(8), 729-36 | Outcome
1687 | Meah, S. (2001). A breastfeeding intervention increased breast feeding and reduced GI tract infections and atopic eczema Evidence Based Nursing, #volume#(#issue#), 106-106 1p | Study design
1688 | Megeid, F. Y. A.,Bakeit, Z. A. N.,Karim, B. O. I. A. A. (2011). Early introduction of cow’s milk and short duration of breastfeeding is associated with increasing risk of juvenile diabetes World Journal of Medical Sciences, 6(2), 54-60 | Study design
1689 | Megraud, F.,Boudraa, G.,Bessaoud, K.,Bensid, S.,Dabis, F.,Soltana, R.,Touhami, M. (1990). Incidence of Campylobacter infection in infants in western Algeria and the possible protective role of breast feeding Epidemiol Infect, 105(1), 73-8 | Study design, Size of study groups
1690 | Meinzen-Derr, J. K.,Guerrero, M. L.,Altaye, M.,Ortega-Gallegos, H.,Ruiz-Palacios, G. M.,Morrow, A. L. (2006). Risk of infant anemia is associated with exclusive breast-feeding and maternal anemia in a Mexican cohort J Nutr, 136(2), 452-8 | Intervention/exposure
1691 | Meinzen-Derr, J. K.,Guerrero, M. L.,Altaye, M.,Ruiz-Palacios, G. M.,Morrow, A. L. (2004). Duration of exclusive breastfeeding and risk of anemia in a cohort of Mexican infants Adv Exp Med Biol, 554(#issue#), 395-8 | Intervention/exposure, Publication status
1692 | Mellander, M.,Noren, J. G.,Freden, H.,Kjellmer, I. (1982). Mineralization defects in deciduous teeth of low birthweight infants Acta Paediatr Scand, 71(5), 727-33 | Participant health, Intervention/exposure
1693 | Meloni, T.,Marinaro, A. M.,Mannazzu, M. C.,Ogana, A.,La Vecchia, C.,Negri, E.,Colombo, C. (1997). IDDM and early infant feeding. Sardinian case-control study Diabetes Care, 20(3), 340-2 | Outcome
1694 | Melville B (1990). The high cost of artificial feeding in Jamaica and its implications for child health West Indian Med J, 39(#issue#), 203-4 | Study design
1695 | Mendelson, M.,Cloutier, J.,Spence, L.,Sellers, E.,Taback, S.,Dean, H. (2011). Obesity and type 2 diabetes mellitus in a birth cohort of First Nation children born to mothers with pediatric-onset type 2 diabetes Pediatr Diabetes, 12(3 Pt 2), 219-28 | Size of study groups, Intervention/exposure
1696 | Mendez, M. A.,Torrent, M.,Julvez, J.,Ribas-Fito, N.,Kogevinas, M.,Sunyer, J. (2009). Maternal fish and other seafood intakes during pregnancy and child neurodevelopment at age 4 years Public Health Nutr, 12(10), 1702-10 | Outcome
1697 | Menihan, C. A.,Phipps, M.,Weitzen, S. (2006). Fetal heart rate patterns and sudden infant death syndrome J Obstet Gynecol Neonatal Nurs, 35(1), 116-22 | Intervention/exposure
1698 | Mennella, J. A.,Trabulsi, J. C.,Papas, M. A. (2015). Effects of cow milk versus extensive protein hydrolysate formulas on infant cognitive development Amino Acids, #volume#(#issue#), #Pages# | Intervention/exposure
1699 | Merewood, A.,Mehta, S. D.,Grossman, X.,Chen, T. C.,Mathieu, J.,Holick, M. F.,Bauchner, H. (2012). Vitamin D status among 4-month-old infants in New England: a prospective cohort study J Hum Lact, 28(2), 159-66 | Intervention/exposure
1700 | Merlob, P.,Aloni, R.,Prager, H.,Jelin, N.,Idel, M.,Kotona, J. (1994). Continued weight loss in the newborn during the third day of life as an indicator of early weaning Israel Journal of Medical Sciences, 30(8), 646-648 | Intervention/exposure, Outcome
1701 | Merlob, P.,Stahl, B.,Sulkes, J. (2004). Paroxetine during breast-feeding: infant weight gain and maternal adherence to counsel Eur J Pediatr, 163(3), 135-9 | Outcome
1702 | Merrett, T. G.,Burr, M. L.,Butland, B. K.,Merrett, J.,Miskelly, F. G.,Vaughan Williams, E. (1988). Infant feeding and allergy: 12-month prospective study of 500 babies born into allergic families. Review 53 refs Annals of allergy, 61(6 (Pt 2)), 13-20 | Redundant data with another study
1703 | Metcalfe, D. D. (1984). Food hypersensitivity J Allergy Clin Immunol, 73(6), 749-62 | Study design, Intervention/exposure
1704 | Metzger, M. W.,McDade, T. W. (2010). Breastfeeding as obesity prevention in the United States: a sibling difference model Am J Hum Biol, 22(3), 291-6 | Outcome
1705 | Meyers, A.,Hertzberg, J. (1988). Bottle-feeding and malocclusion: is there an association? Am J Orthod Dentofacial Orthop, 93(2), 149-52 | Study design
1706 | Micali, N.,Simonoff, E.,Treasure, J. (2009). Infant feeding and weight in the first year of life in babies of women with eating disorders J Pediatr, 154(1), 55-60 e1 | Outcome
1707 | Michaelsen KF (2015). 1.1 Child growth World Rev Nutr Diet, 113(#issue#), 1-5 | Publication status
1708 | Michaelsen, K. F. (1997). Nutrition and growth during infancy. The Copenhagen Cohort Study Acta Paediatr Suppl, 420(#issue#), 1-36 | Outcome
1709 | Michaelsen, K. F. (2015). 2.1 Breastfeeding World Rev Nutr Diet, 113(#issue#), 92-6 | Study design
1710 | Michaelsen, K. F.,Larnkjaer, A.,Molgaard, C. (2013). Early diet, insulin-like growth factor-1, growth and later obesity #journal#, 106((Michaelsen K.F., kfm@life.ku.dk; Larnkjaer A.; Molgaard C.) Department of Nutrition Exercise and Sports, Faculty of Science, University of Copenhagen, DK-1958 Frederiksberg C, Denmark), 113-118 | Publication status
1711 | Michaelsen, K. F.,Petersen, S.,Greisen, G.,Thomsen, B. L. (1994). Weight, length, head circumference, and growth velocity in a longitudinal study of Danish infants Dan Med Bull, 41(5), 577-85 | Study design, Intervention/exposure
1712 | Michel, H.,Olabopo, F.,Wang, L.,Nucci, A.,Greenspan, S. L.,Rajakumar, K. (2015). Determinants of 25-hydroxyvitamin D concentrations in infants and toddlers Current Nutrition and Food Science, 11(2), 124-130 | Study design
1713 | Michels, K. B.,Willett, W. C.,Graubard, B. I.,Vaidya, R. L.,Cantwell, M. M.,Sansbury, L. B.,Forman, M. R. (2007). A longitudinal study of infant feeding and obesity throughout life course Int J Obes (Lond), 31(7), 1078-85 | Intervention/exposure
1714 | Michie, C. (2016). Breast feeding could reduce the risk of childhood leukaemias Evid Based Nurs, #volume#(#issue#), #Pages# | Study design
1715 | Michie, C. A.,Gilmour, J. (2001). Breast feeding and the risks of viral transmission Arch Dis Child, 84(5), 381-2 | Study design
1716 | Midodzi, W. K.,Rowe, B. H.,Majaesic, C. M.,Saunders, L. D.,Senthilselvan, A. (2008). Predictors for wheezing phenotypes in the first decade of life Respirology, 13(4), 537-45 | Outcome
1717 | Midodzi, W. K.,Rowe, B. H.,Majaesic, C. M.,Saunders, L. D.,Senthilselvan, A. (2010). Early life factors associated with incidence of physician-diagnosed asthma in preschool children: results from the Canadian Early Childhood Development cohort study J Asthma, 47(1), 7-13 | Outcome
1718 | Midtvedt, A. C.,Midtvedt, T. (1992). Production of short chain fatty acids by the intestinal microflora during the first 2 years of human life J Pediatr Gastroenterol Nutr, 15(4), 395-403 | Size of study groups, Outcome
1719 | Midwinter, R. E.,Morris, A. F.,Colley, J. R. (1987). Infant feeding and atopy Arch Dis Child, 62(9), 965-7 | Study design, Intervention/exposure
1720 | Mihrshahi, S.,Ampon, R.,Webb, K.,Almqvist, C.,Kemp, A. S.,Hector, D.,Marks, G. B. (2007). The association between infant feeding practices and subsequent atopy among children with a family history of asthma Clin Exp Allergy, 37(5), 671-9 | Outcome
1721 | Mihrshahi, S.,Battistutta, D.,Magarey, A.,Daniels, L. A. (2011). Determinants of rapid weight gain during infancy: baseline results from the NOURISH randomised controlled trial BMC Pediatr, 11(#issue#), 99 | Intervention/exposure
1722 | Mikiel-Kostyra, K.,Mazur, J. (1999). Hospital policies and their influence on newborn body weight Acta Paediatr, 88(1), 72-5 | Study design, Intervention/exposure
1723 | Milaat, W. A.,Elassouli, S. M. (1995). Epidemiology of diarrhoea in two major cities in Saudi Arabia J Commun Dis, 27(2), 84-91 | Study design, Participant health
1724 | Milankov, O.,Bjelica, M.,Savic, R. (2014). What kind of milk can prevent infant’s sideropenic anemia--comparative study Med Pregl, 67(5-6), 167-71 | Study design, Participant health
1725 | Miliku, K.,Voortman, T.,Bakker, H.,Hofman, A.,Franco, O. H.,Jaddoe, V. W. (2015). Infant Breastfeeding and Kidney Function in School-Aged Children Am J Kidney Dis, 66(3), 421-8 | Outcome
1726 | Miljanovic, O.,Cikota-Aleksic, B.,Likic, D.,Vojvodic, D.,Jovicevic, O.,Magic, Z. (2016). Association of cytokine gene polymorphisms and risk factors with otitis media proneness in children Eur J Pediatr, #volume#(#issue#), #Pages# | Outcome
1727 | Millard, A. V.,Graham, M. A. (1985). Abrupt weaning reconsidered: evidence from central Mexico J Trop Pediatr, 31(4), 229-34 | Study design, Outcome
1728 | Miller, J. E. (2001). Predictors of asthma in young children: does reporting source affect our conclusions? Am J Epidemiol, 154(3), 245-50 | Outcome
1729 | Miller, M. R.,Seifert, J.,Szabo, N. J.,Clare-Salzler, M.,Rewers, M.,Norris, J. M. (2010). Erythrocyte membrane fatty acid content in infants consuming formulas supplemented with docosahexaenoic acid (DHA) and arachidonic acid (ARA): an observational study Matern Child Nutr, 6(4), 338-46 | Intervention/exposure
1730 | Mills, A. F. (1990). Surveillance for anaemia: risk factors in patterns of milk intake Arch Dis Child, 65(4), 428-31 | Study design, Size of study groups
1731 | Mills, R. P. (1987). Persistent middle ear effusions in children with recurrent acute otitis media Clin Otolaryngol Allied Sci, 12(2), 97-101 | Participant health
1732 | Milner, J. D.,Stein, D. M.,McCarter, R.,Moon, R. Y. (2004). Early infant multivitamin supplementation is associated with increased risk for food allergy and asthma Pediatrics, 114(1), 27-32 | Outcome
1733 | Milnes, A. R.,Bowden, G. H. (1985). The microflora associated with developing lesions of nursing caries Caries Res, 19(4), 289-97 | Study design, Size of study groups
1734 | Mimouni-Bloch, A.,Kachevanskaya, A.,Mimouni, F. B.,Shuper, A.,Raveh, E.,Linder, N. (2013). Breastfeeding may protect from developing attention-deficit/hyperactivity disorder Breastfeed Med, 8(4), 363-7 | Outcome
1735 | Minchin, M. (1987). Infant formula: a mass, uncontrolled trial in perinatal care Birth, 14(1), 25-35 | Study design
1736 | Minchin, M. (2000). Artificial feeding and risk Pract Midwife, 3(3), 18-20 | Study design
1737 | Mindru, D. E.,Moraru, E. (2012). Risk factors and their implications in the epidemiology of pediatric obesity Rev Med Chir Soc Med Nat Iasi, 116(3), 739-45 | Study design
1738 | Minet, J. C.,Bisse, E.,Aebischer, C. P.,Beil, A.,Wieland, H.,Lutschg, J. (2000). Assessment of vitamin B-12, folate, and vitamin B-6 status and relation to sulfur amino acid metabolism in neonates Am J Clin Nutr, 72(3), 751-7 | Study design
1739 | Miranda, B. H.,Milroy, C. J. (2010). A quick snip - A study of the impact of outpatient tongue tie release on neonatal growth and breastfeeding J Plast Reconstr Aesthet Surg, 63(9), e683-5 | Intervention/exposure
1740 | Miskelly, F. G.,Burr, M. L.,Vaughan-Williams, E.,Fehily, A. M.,Butland, B. K.,Merrett, T. G. (1988). Infant feeding and allergy Arch Dis Child, 63(4), 388-93 | Outcome
1741 | Misra, S.,Sabui, T. K.,Basu, S.,Pal, N. (2007). A prospective study of rotavirus diarrhea in children under 1 year of age Clin Pediatr (Phila), 46(8), 683-8 | Country
1742 | Mitchell, E. A.,Blair, P. S. (2012). SIDS prevention: 3000 lives saved but we can do better N Z Med J, 125(1359), 50-7 | Study design
1743 | Mitchell, E. A.,Esmail, A.,Jones, D. R.,Clements, M. (1996). Do differences in the prevalence of risk factors explain the higher mortality from sudden infant death syndrome in New Zealand compared with the UK? N Z Med J, 109(1030), 352-5 | Study design
1744 | Mitchell, E. A.,Scragg, R.,Stewart, A. W.,Becroft, D. M.,Taylor, B. J.,Ford, R. P.,Hassall, I. B.,Barry, D. M.,Allen, E. M.,Roberts, A. P. (1991). Results from the first year of the New Zealand cot death study N Z Med J, 104(906), 71-6 | Outcome
1745 | Mitchell, E. A.,Stewart, A. W.,Scragg, R.,Ford, R. P.,Taylor, B. J.,Becroft, D. M.,Thompson, J. M.,Hassall, I. B.,Barry, D. M.,Allen, E. M.,et al, (1993). Ethnic differences in mortality from sudden infant death syndrome in New Zealand BMJ, 306(6869), 13-6 | Study design, Intervention/exposure
1746 | Mitchell, E. A.,Thompson, J. M. (2001). Parental reported apnoea, admissions to hospital and sudden infant death syndrome Acta Paediatr, 90(4), 417-22 | Study design, Intervention/exposure
1747 | Mitchell, E. A.,Tuohy, P. G.,Brunt, J. M.,Thompson, J. M.,Clements, M. S.,Stewart, A. W.,Ford, R. P.,Taylor, B. J. (1997). Risk factors for sudden infant death syndrome following the prevention campaign in New Zealand: a prospective study Pediatrics, 100(5), 835-40 | Outcome
1748 | Mittal, S. K. (1988). Bowel pattern and weight gain in breast fed infants Indian Pediatr, 25(2), 216-7 | Study design
1749 | Mittal, S. K.,Kanwar, A.,Varghese, A.,Ramachandran, V. G. (1983). Gut flora in breast and bottle fed infants with and without diarrhea Indian Pediatr, 20(1), 21-6 | Country
1750 | Miyake, Y.,Tanaka, K.,Sasaki, S.,Kiyohara, C.,Ohya, Y.,Fukushima, W.,Yokoyama, T.,Hirota, Y. (2008). Breastfeeding and the risk of wheeze and asthma in Japanese infants: the Osaka Maternal and Child Health Study Pediatr Allergy Immunol, 19(6), 490-6 | Study design
1751 | Miyake, Y.,Tanaka, K.,Sasaki, S.,Kiyohara, C.,Ohya, Y.,Fukushima, W.,Yokoyama, T.,Hirota, Y. (2009). Breastfeeding and atopic eczema in Japanese infants: The Osaka Maternal and Child Health Study Pediatr Allergy Immunol, 20(3), 234-41 | Outcome
1752 | Miyamoto, S.,Murotani, K.,Yanagawa, T.,Kato, A.,Matsunaga, S. (2010). Relationship of low lean body mass with body weight increase until one year of age and current lifestyles in Japanese young women J Hum Ergol (Tokyo), 39(1), 45-51 | Study design, Intervention/exposure
1753 | Mize, C. E.,Uauy, R.,Kramer, R.,Benser, M.,Allen, S.,Grundy, S. M. (1995). Lipoprotein-cholesterol responses in healthy infants fed defined diets from ages 1 to 12 months: comparison of diets predominant in oleic acid versus linoleic acid, with parallel observations in infants fed a human milk-based diet J Lipid Res, 36(6), 1178-87 | Outcome
1754 | Mizuno, K.,Ueda, A.,Takeuchi, T. (2002). Effects of different fluids on the relationship between swallowing and breathing during nutritive sucking in neonates Biol Neonate, 81(1), 45-50 | Study design, Size of study groups
1755 | Modi, N.,Thomas, E. L.,Harrington, T. A.,Uthaya, S.,Dore, C. J.,Bell, J. D. (2006). Determinants of adiposity during preweaning postnatal growth in appropriately grown and growth-restricted term infants Pediatr Res, 60(3), 345-8 | Size of study groups
1756 | Moimaz, S. A.,Garbin, A. J.,Lima, A. M.,Lolli, L. F.,Saliba, O.,Garbin, C. A. (2014). Longitudinal study of habits leading to malocclusion development in childhood BMC Oral Health, 14(#issue#), 96 | Outcome
1757 | Mok, J. Y.,Simpson, H. (1982). Outcome of acute lower respiratory tract infection in infants: preliminary report of seven-year follow-up study Br Med J (Clin Res Ed), 285(6338), 333-7 | Study design, Size of study groups
1758 | Molgaard, C.,Larnkjaer, A.,Mark, A. B.,Michaelsen, K. F. (2011). Are early growth and nutrition related to bone health in adolescence? The Copenhagen Cohort Study of infant nutrition and growth Am J Clin Nutr, 94(6 Suppl), 1865S-1869S | Outcome
1759 | Molla, A. M.,Badawi, M. H.,Al-Yaish, S.,Sharma, P.,El-Salam, R. S.,Molla, A. M. (2000). Risk factors for nutritional rickets among children in Kuwait Pediatrics International, 42(3), 280-284 | Intervention/exposure
1760 | Mollborg, P.,Wennergren, G.,Almqvist, P.,Alm, B. (2015). Bed sharing is more common in sudden infant death syndrome than in explained sudden unexpected deaths in infancy Acta Paediatr, 104(8), 777-83 | Outcome
1761 | Molokhia, E. A.,Perkins, A. (2008). Preventing cancer Prim Care, 35(4), 609-23 | Study design
1762 | Monobe, H.,Ishibashi, T.,Fujishiro, Y.,Shinogami, M.,Yano, J. (2003). Factors associated with poor outcome in children with acute otitis media Acta Otolaryngol, 123(5), 564-8 | Study design
1763 | Monson, T. P. (1986). Pediatric viral gastroenteritis Am Fam Physician, 34(1), 95-9 | Study design
1764 | Montagu, A. (1984). The skin, touch, and human development Clin Dermatol, 2(4), 17-26 | Study design
1765 | Monte, W. C.,Johnston, C. S.,Roll, L. E. (1994). Bovine serum albumin detected in infant formula is a possible trigger for insulin-dependent diabetes mellitus J Am Diet Assoc, 94(3), 314-6 | Study design, Non-human sample
1766 | Montefort, S.,Muscat, H. A.,Caruana, S.,Lenicker, H. (2002). Allergic conditions in 5-8-year-old Maltese schoolchildren: prevalence, severity, and associated risk factors [ISAAC] Pediatr Allergy Immunol, 13(2), 98-104 | Study design
1767 | Monterrosa, E. C.,Frongillo, E. A.,Vasquez-Garibay, E. M.,Romero-Velarde, E.,Casey, L. M.,Willows, N. D. (2008). Predominant breast-feeding from birth to six months is associated with fewer gastrointestinal infections and increased risk for iron deficiency among infants J Nutr, 138(8), 1499-504 | Intervention/exposure
1768 | Montgomery, S. M.,Ehlin, A.,Sacker, A. (2006). Breast feeding and resilience against psychosocial stress Arch Dis Child, 91(12), 990-4 | Outcome
1769 | Moodley, A.,Spector, S. A. (2015). Single high-dose vitamin D at birth corrects vitamin D deficiency in infants in Mexico Int J Food Sci Nutr, 66(3), 336-41 | Size of study groups, Intervention/exposure
1770 | Moon, R. Y.,Tanabe, K. O.,Yang, D. C.,Young, H. A.,Hauck, F. R. (2012). Pacifier use and SIDS: evidence for a consistently reduced risk Maternal and child health journal, 16(3), 609-614 | Outcome
1771 | Moore, Elizabeth R. (2013). Early Skin-To-Skin Contact for Mothers and Their Healthy Newborn Infants JOGNN: Journal of Obstetric, Gynecologic & Neonatal Nursing, 42(#issue#), S86-S86 1p | Study design
1772 | Moore, S. R.,Lima, N. L.,Soares, A. M.,Oria, R. B.,Pinkerton, R. C.,Barrett, L. J.,Guerrant, R. L.,Lima, A. A. (2010). Prolonged episodes of acute diarrhea reduce growth and increase risk of persistent diarrhea in children Gastroenterology, 139(4), 1156-64 | Outcome
1773 | Moore, W. J.,Midwinter, R. E.,Morris, A. F.,Colley, J. R.,Soothill, J. F. (1985). Infant feeding and subsequent risk of atopic eczema Arch Dis Child, 60(8), 722-6 | Size of study groups, Intervention/exposure
1774 | Mora Urda, A. I.,Pereira da Silva, R.,Bisi Molina Mdel, C.,Bresciani Salaroli, L.,Montero Lopez Mdel, P. (2015). [RELATIONSHIP BETWEEN PATTERNS OF BREASTFEEDING AND BLOOD PRESSURE IN BRAZILIAN AND SPANISH SCHOOLCHILDREN] Nutr Hosp, 32(4), 1568-75 | Language
1775 | Moraeus, L.,Lissner, L.,Yngve, A.,Poortvliet, E.,Al-Ansari, U.,Sjoberg, A. (2012). Multi-level influences on childhood obesity in Sweden: societal factors, parental determinants and child’s lifestyle Int J Obes (Lond), 36(7), 969-76 | Study design, Intervention/exposure
1776 | Morale, S. E.,Hoffman, D. R.,Castañeda, Y. S.,Wheaton, D. H.,Burns, R. A.,Birch, E. E. (2005). Duration of long-chain polyunsaturated fatty acids availability in the diet and visual acuity Early Human Development, 81(2), 197-203 | Outcome
1777 | Morales, E.,Bustamante, M.,Gonzalez, J. R.,Guxens, M.,Torrent, M.,Mendez, M.,Garcia-Esteban, R.,Julvez, J.,Forns, J.,Vrijheid, M.,Molto-Puigmarti, C.,Lopez-Sabater, C.,Estivill, X.,Sunyer, J. (2011). Genetic variants of the FADS gene cluster and ELOVL gene family, colostrums LC-PUFA levels, breastfeeding, and child cognition PLoS One, 6(2), e17181 | Size of study groups
1778 | Morales, E.,Garcia-Esteban, R.,Guxens, M.,Guerra, S.,Mendez, M.,Molto-Puigmarti, C.,Lopez-Sabater, M. C.,Sunyer, J. (2012). Effects of prolonged breastfeeding and colostrum fatty acids on allergic manifestations and infections in infancy Clin Exp Allergy, 42(6), 918-28 | Outcome
1779 | Moran, J. R. (1992). Effects of prolonged exposure to partially hydrolyzed milk protein J Pediatr, 121(5 Pt 2), S90-4 | Outcome
1780 | Moreno, M. (2014). Early infant feeding and obesity risk JAMA Pediatr, 168(11), 1084 | Study design
1781 | Morgan, C.,Davies, L.,Corcoran, F.,Stammers, J.,Colley, J.,Spencer, S. A.,Hull, D. (1998). Fatty acid balance studies in term infants fed formula milk containing long-chain polyunsaturated fatty acids Acta Paediatr, 87(2), 136-42 | Size of study groups
1782 | Morgan, J. B.,Mumford, P. M. (1980). A follow-up study of nutrition and anthropometry in pre-school children Proc Nutr Soc, 39(1), 5A | Publication status
1783 | Morgan, J.,Taylor, A.,Fewtrell, M. (2004). Meat consumption is positively associated with psychomotor outcome in children up to 24 months of age J Pediatr Gastroenterol Nutr, 39(5), 493-8 | Outcome
1784 | Morin, K. H. (2009). Breastfeeding immediately after birth MCN Am J Matern Child Nurs, 34(1), 63 | Study design
1785 | Morley, R. (1998). Iron supplemented follow-on formula and growth and development: a randomised trial [abstract] Proc Nutr Soc Aust, 22(#issue#), 288 | Publication status
1786 | Morley-Peet, P. (1983). Enteropathogenic Escherichia coli Nurs Times, 79(23), 24-7 | Study design
1787 | Moro, D. (1995). Birthweight and breast feeding of babies born during the war in one municipal area of Sarajevo Eur J Clin Nutr, 49 Suppl 2(#issue#), S37-9 | Intervention/exposure, Outcome
1788 | Morris, S. S.,Grantham-McGregor, S. M.,Lira, P. I.,Assuncao, A. M.,Ashworth, A. (1999). Effect of breastfeeding and morbidity on the development of low birthweight term babies in Brazil Acta Paediatr, 88(10), 1101-6 | Intervention/exposure
1789 | Morrow, A. L. (2011). Infant feeding in the 21st century J Pediatr Health Care, 25(3), 195-7 | Study design, Outcome
1790 | Morrow, A. L.,Guerrero, M. L. (2001). From bioactive substances to research on breast-feeding promotion Adv Exp Med Biol, 501(#issue#), 447-55 | Study design, Intervention/exposure
1791 | Morrow, A. L.,Reves, R. R.,West, M. S.,Guerrero, M. L.,Ruiz-Palacios, G. M.,Pickering, L. K. (1992). Protection against infection with Giardia lamblia by breast-feeding in a cohort of Mexican infants J Pediatr, 121(3), 363-70 | Intervention/exposure
1792 | Morrow-Tlucak, M.,Haude, R. H.,Ernhart, C. B. (1988). Breastfeeding and cognitive development in the first 2 years of life Soc Sci Med, 26(6), 635-9 | Outcome
1793 | Mortensen, E. L.,Michaelsen, K. F.,Sanders, S. A.,Reinisch, J. M. (2002). The association between duration of breastfeeding and adult intelligence JAMA, 287(18), 2365-71 | Outcome
1794 | Moschonis, G.,Grammatikaki, E.,Manios, Y. (2008). Perinatal predictors of overweight at infancy and preschool childhood: the GENESIS study Int J Obes (Lond), 32(1), 39-47 | Study design
1795 | Moss, B. G.,Yeaton, W. H. (2014). Early childhood healthy and obese weight status: potentially protective benefits of breastfeeding and delaying solid foods Matern Child Health J, 18(5), 1224-32 | Outcome
1796 | Mo-Suwan, L.,Junjana, C. (1991). Breast-feeding and infant growth in the first six months J Med Assoc Thai, 74(9), 386-90 | Intervention/exposure
1797 | Motil, K. J.,Sheng, H. P.,Montandon, C. M.,Wong, W. W. (1997). Human milk protein does not limit growth of breast-fed infants J Pediatr Gastroenterol Nutr, 24(1), 10-7 | Size of study groups
1798 | Motta, M.,Tincani, A.,Faden, D.,Zinzini, E.,Lojacono, A.,Marchesi, A.,Frassi, M.,Biasini, C.,Zatti, S.,Chirico, G. (2005). Follow-up of infants exposed to hydroxychloroquine given to mothers during pregnancy and lactation J Perinatol, 25(2), 86-9 | Size of study groups
1799 | Moxley, S.,Avni, G.,Brydon, S.,Kennedy, M. (1998). Breastfeeding and shorter hospital stays Can Nurse, 94(7), 35-9 | Study design
1800 | Mueller, W. H.,Pollitt, E. (1982). The Bacon Chow study: effects of nutrition supplementation on sibling-sibling anthropometric correlations Hum Biol, 54(3), 455-68 | Study design, Intervention/exposure
1801 | Mughal, M. Z.,Salama, H.,Greenaway, T.,Laing, I.,Mawer, E. B. (1999). Lesson of the week: florid rickets associated with prolonged breast feeding without vitamin D supplementation Bmj, 318(7175), 39-40 | Study design
1802 | Mughini-Gras, L.,Pijnacker, R.,Heusinkveld, M.,Enserink, R.,Zuidema, R.,Duizer, E.,Kortbeek, T.,van Pelt, W. (2016). Societal Burden and Correlates of Acute Gastroenteritis in Families with Preschool Children Sci Rep, 6(#issue#), 22144 | Study design
1803 | Muiño, A.,Menezes, A. M. B.,Reichert, F. F.,Duquia, R. P.,Chatkin, M. (2008). Wheezing phenotypes from birth to adolescence: A cohort study in Pelotas, Brazil, 1993-2004 Jornal Brasileiro de Pneumologia, 34(6), 347-355 | Intervention/exposure, Outcome
1804 | Muirhead, P. (1998). A randomized controlled study of the effect of organised peer support on the duration of breast feeding and the consequences for infant morbidity Personal communication, #volume#(#issue#), #Pages# | Study design
1805 | Mukherjee, D.,Stephens, D. (1997). Otitis media with effusion in intellectually disabled children Journal of Audiological Medicine, 6(1), 10-23 | Study design, Intervention/exposure
1806 | Mukhopadhya, J. (2001). Acute Respiratory Infection among children in an Air Force Community Medical Journal Armed Forces India, 57(4), 309-311 | Country
1807 | Mukhopadhyay, S.,Lieberman, E. S.,Puopolo, K. M.,Riley, L. E.,Johnson, L. C. (2015). Effect of early-onset sepsis evaluations on in-hospital breastfeeding practices among asymptomatic term neonates Hosp Pediatr, 5(4), 203-10 | Outcome
1808 | Mulhall AL (1984). Breast feeding: a challenge for midwives World Ir Nurs, 13(#issue#), 8-9 | Publication status
1809 | Muller, M. (1996). Nursing-bottle syndrome: risk factors ASDC J Dent Child, 63(1), 42-50 | Study design
1810 | Mulrine, H. M.,Skeaff, S. A.,Ferguson, E. L.,Gray, A. R.,Valeix, P. (2010). Breast-milk iodine concentration declines over the first 6 mo postpartum in iodine-deficient women Am J Clin Nutr, 92(4), 849-56 | Size of study groups
1811 | Munir M,Mustadjab I,Rampengan TH,Wulur FH (1983). Problem of infant feeding practices: implications for immediate action Paediatr Indones, 23(#issue#), 32-46 | Country
1812 | Munir, M. (1985). Infantile diarrhoea: breast and bottle feeding compared with special reference to their clinical role Paediatr Indones, 25(5-6), 100-6 | Study design, Participant health
1813 | Muniz, L. C.,Menezes, A. M.,Assuncao, M. C.,Wehrmeister, F. C.,Martinez-Mesa, J.,Goncalves, H.,Domingues, M. R.,Gigante, D. P.,Horta, B. L.,Barros, F. C. (2015). Breastfeeding and bone mass at the ages of 18 and 30: prospective analysis of live births from the Pelotas (Brazil) 1982 and 1993 cohorts PLoS One, 10(4), e0122759 | Outcome
1814 | Munns, C. F.,Simm, P. J.,Rodda, C. P.,Garnett, S. P.,Zacharin, M. R.,Ward, L. M.,Geddes, J.,Cherian, S.,Zurynski, Y.,Cowell, C. T. (2012). Incidence of vitamin D deficiency rickets among Australian children: an Australian Paediatric Surveillance Unit study Med J Aust, 196(7), 466-8 | Participant health, Intervention/exposure
1815 | Murdoch, W. (1980). Breast feeding Cent Afr J Med, 26(4), 95-7 | Study design
1816 | Murphy RM (1981). The hidden epidemic Can Nurse, 77(#issue#), 42-3 | Study design
1817 | Murrell, W. G.,Stewart, B. J.,O’Neill, C.,Siarakas, S.,Kariks, S. (1993). Enterotoxigenic bacteria in the sudden infant death syndrome Journal of Medical Microbiology, 39(2), 114-127 | Intervention/exposure
1818 | Musaad, S. M.,Donovan, S. M.,Fiese, B. H. (2015). Parental perception of child weight in the first two years-of-life: a potential link between infant feeding and preschoolers’ diet Appetite, 91(#issue#), 90-100 | Study design
1819 | Myres AW (1983). The national breast-feeding promotion program. Part 2. Public information phase--a note on its development, distribution and impact Can J Public Health, 74(#issue#), 404-8 | Study design, Outcome
1820 | Myres AW,Watson J,Harrison C (1981). The national breast-feeding promotion program 1. Professional phase--a note on its development, distribution and impact Can J Public Health, 72(#issue#), 307-11 | Study design
1821 | Myres, A. W. (1988). Tradition and technology in infant feeding--achieving the best of both worlds Can J Public Health, 79(2), 78-80 | Study design
1822 | Nafstad, P.,Jaakkola, J. J.,Hagen, J. A.,Botten, G.,Kongerud, J. (1996). Breastfeeding, maternal smoking and lower respiratory tract infections Eur Respir J, 9(12), 2623-9 | Outcome
1823 | Nafstad, P.,Jaakkola, J. J.,Hagen, J. A.,Pedersen, B. S.,Qvigstad, E.,Botten, G.,Kongerud, J. (1997). Weight gain during the first year of life in relation to maternal smoking and breast feeding in Norway J Epidemiol Community Health, 51(3), 261-5 | Outcome
1824 | Nagahara, K.,Dobashi, K.,Itabashi, K. (2013). Feeding choice has a gender-associated effect on infant growth Pediatr Int, 55(4), 481-7 | Intervention/exposure
1825 | Nagendra, R.,Viswanatha, S.,Arun Kumar, S.,Krishna Murthy, B.,Venkat Rao, S. (1995). Effect of feeding milk formula containing lactulose to infants on faecal bifidobacterial flora Nutrition Research, 15(1), 15-24 | Size of study groups
1826 | Naggan, L.,Forman, M. R.,Sarov, B.,Lewando-Hundt, G.,Zangwill, L.,Chang, D.,Berendes, H. W. (1991). The Bedouin Infant Feeding Study: study design and factors influencing the duration of breast feeding Paediatr Perinat Epidemiol, 5(4), 428-44 | Outcome
1827 | Najada, A. S.,Habashneh, M. S.,Khader, M. (2004). The frequency of nutritional rickets among hospitalized infants and its relation to respiratory diseases J Trop Pediatr, 50(6), 364-8 | Study design, Participant health
1828 | Nakamura, Y.,Oki, I.,Tanihara, S.,Ojima, T.,Ito, Y.,Yamazaki, O.,Iwama, M.,Tabata, Y.,Katsuyama, K.,Sasai, Y.,Nakagawa, M.,Matsushita, A.,Hossaka, K.,Sato, J.,Hidaka, Y.,Uda, H.,Nakamata, K.,Yanagawa, H. (2000). Relationship between breast milk feeding and atopic dermatitis in children J Epidemiol, 10(2), 74-8 | Study design
1829 | Nakao H (1988). Nutritional significance of human milk vitamin D in neonatal period Kobe J Med Sci, 34(#issue#), 121-8 | Size of study groups
1830 | Nakao, R. M. (1988). Effects of an education program on the health and illness profile of rural breast-fed babies Philipp J Nurs, 58(2), 12-8 | Country
1831 | Nambiar, H. K. (1984). Acute diarrhoeal diseases: a malady in children Nurs J India, 75(8), 179 | Study design
1832 | Nambiar, Smita,Truby, Helen,Davies, Peter S. W. (2013). Exploring the influence of breastfeeding on abdominal adiposity in young children using the waist to height ratio Nutrition & Dietetics, 70(2), 146-152 7p | Study design
1833 | Narayan, N. R.,Mendez-Lagares, G.,Ardeshir, A.,Lu, D.,Van Rompay, K. K.,Hartigan-O’Connor, D. J. (2015). Persistent effects of early infant diet and associated microbiota on the juvenile immune system Gut Microbes, 6(4), 284-9 | Non-human sample
1834 | Narayanan, I.,Gupta, J. (1989). Human milk and neonatal infections Acta Paediatr Scand Suppl, 351(#issue#), 126-30 | Country, Outcome
1835 | Narayanan, I.,Prakash, K.,Murthy, N. S.,Gujral, V. V. (1984). Randomised controlled trial of effect of raw and holder pasteurised human milk and of formula supplements on incidence of neonatal infection Lancet, 2(8412), 1111-3 | Country
1836 | Narayanan, I.,Singh, S.,Mathur, R.,Jain, B. K. (1989). Ear infection and infant feeding practices Indian J Pediatr, 56(3), 399-402 | Country
1837 | Narchi, H.,Kochiyil, J.,Zayed, R.,Abdulrazzak, W.,Agarwal, M. (2010). Maternal vitamin D status throughout and after pregnancy J Obstet Gynaecol, 30(2), 137-42 | Outcome
1838 | Narchi, H.,Kochiyil, J.,Zayed, R.,Abdulrazzak, W.,Agarwal, M. (2011). Longitudinal study of vitamin D status in the 1st 6 months of life Ann Trop Paediatr, 31(3), 225-30 | Study design, Size of study groups
1839 | Narese, F.,Puccio, G.,Mazzucco, W.,Falzone, A.,Venturella, V.,Narese, D.,Capra, E. (2011). Earlier appearance of the ossification center of the femoral head in breast-fed versus formula-fed infants Nutrition, 27(11-12), 1108-11 | Study design
1840 | Nascimento Souza, Maria Helena,Aparecida Barbosa Nogueira, Josiê Neiber,Domingues Sodré, Vitória Regina (2015). MONITORING THE NUTRITIONAL AND HEALTH STATUS OF CHILDREN WHO ATTEND A COMMUNITY NURSERY Journal of Nursing UFPE / Revista de Enfermagem UFPE, 9(5), 7862-7868 7p | Study design, Intervention/exposure
1841 | Nassar, M. F.,Younis, N. T.,El-Arab, S. E.,Fawzi, F. A. (2011). Neuro-developmental outcome and brain-derived neurotrophic factor level in relation to feeding practice in early infancy Matern Child Nutr, 7(2), 188-97 | Study design, Size of study groups
1842 | Nauta, A. (2012). Specific nutritional concepts & clinical evidence in the management of allergy Asian Pacific Journal of Allergy and Immunology, 30(4 SUPPL), S21-S24 | Study design
1843 | Navarro, J. I.,Sigulem, D. M.,Ferraro, A. A.,Polanco, J. J.,Barros, A. J. (2013). The double task of preventing malnutrition and overweight: a quasi-experimental community-based trial BMC Public Health, 13(#issue#), 212 | Intervention/exposure
1844 | Nelson, C. M.,Innis, S. M. (1999). Plasma lipoprotein fatty acids are altered by the positional distribution of fatty acids in infant formula triacylglycerols and human milk Am J Clin Nutr, 70(1), 62-9 | Size of study groups
1845 | Nelson, C. M.,Innis, S. M.,Walsen, P.,Whitfield, M. (2002). Prospective measures of visual and cognitive development in term gestation breast-fed and formula-fed infants to 18 months of age Pediatric research, 2(#issue#), 315a | Publication status
1846 | Nelson, E. A.,Yu, L. M.,Wong, D.,Wong, H. Y.,Yim, L. (2004). Rolling over in infants: age, ethnicity, and cultural differences Dev Med Child Neurol, 46(10), 706-9 | Size of study groups
1847 | Nelson, J. D. (1985). Prevention of gastrointestinal infections Pediatr Infect Dis, 4(4), 431-4 | Study design, Intervention/exposure
1848 | Nelson, M. C.,Gordon-Larsen, P.,Adair, L. S. (2005). Are adolescents who were breast-fed less likely to be overweight? Analyses of sibling pairs to reduce confounding Epidemiology, 16(2), 247-53 | Outcome
1849 | Nelson, S. E.,Rogers, R. R.,Ziegler, E. E.,Fomon, S. J. (1989). Gain in weight and length during early infancy Early Hum Dev, 19(4), 223-39 | Outcome
1850 | Nelson, S.,Albert, J. M.,Soderling, E.,Malik, A.,Curtan, S.,Geng, C.,Milgrom, P. (2014). Increased number of teeth predict acquisition of mutans streptococci in infants Eur J Oral Sci, 122(5), 346-52 | Outcome
1851 | Nentwich, I.,Michkova, E.,Nevoral, J.,Urbanek, R.,Szepfalusi, Z. (2001). Cow’s milk-specific cellular and humoral immune responses and atopy skin symptoms in infants from atopic families fed a partially (pHF) or extensively (eHF) hydrolyzed infant formula Allergy, 56(12), 1144-56 | Size of study groups
1852 | Nery Cde, G.,Buranello, F. S.,Pereira, C.,Di Francesco, R. C. (2010). Otitis media with effusion and dental occlusion: is there any relationship? Eur J Paediatr Dent, 11(3), 132-6 | Participant health, Intervention/exposure
1853 | Neutzling, M. B.,Hallal, P. R.,Araujo, C. L.,Horta, B. L.,Vieira Mde, F.,Menezes, A. M.,Victora, C. G. (2009). Infant feeding and obesity at 11 years: prospective birth cohort study Int J Pediatr Obes, 4(3), 143-9 | Outcome
1854 | Neves, A. B.,Lobo, L. A.,Pinto, K. C.,Pires, E. S.,Requejo, M.,Maia, L. C.,Antonio, A. G. (2015). Comparison between Clinical Aspects and Salivary Microbial Profile of Children with and without Early Childhood Caries: A Preliminary Study J Clin Pediatr Dent, 39(3), 209-14 | Study design, Size of study groups
1855 | Newburg, D. S.,Ruiz-Palacios, G. M.,Altaye, M.,Chaturvedi, P.,Guerrero, M. L.,Meinzen-Derr, J. K.,Morrow, A. L. (2004). Human milk alphal,2-linked fucosylated oligosaccharides decrease risk of diarrhea due to stable toxin of E. coli in breastfed infants Adv Exp Med Biol, 554(#issue#), 457-61 | Intervention/exposure
1856 | Newman, J. (1995). How breast milk protects newborns Sci Am, 273(6), 76-9 | Study design
1857 | Ng, S. C.,Chong, Y. S.,Rauff, M.,Myo, Z. M.,Nurfarah, C.,Deurenberg, P. R. (2004). The influence of breast feeding compared to formula feeding on infant adiposity Ann Acad Med Singapore, 33(5 Suppl), S75 | Publication status
1858 | Ng, S. C.,Tang, W.,Leong, R. W.,Chen, M.,Ko, Y.,Studd, C.,Niewiadomski, O.,Bell, S.,Kamm, M. A.,de Silva, H. J.,Kasturiratne, A.,Senanayake, Y. U.,Ooi, C. J.,Ling, K. L.,Ong, D.,Goh, K. L.,Hilmi, I.,Ouyang, Q.,Wang, Y. F.,Hu, P.,Zhu, Z.,Zeng, Z.,Wu, K.,Wang, X.,Xia, B.,Li, J.,Pisespongsa, P.,Manatsathit, S.,Aniwan, S.,Simadibrata, M.,Abdullah, M.,Tsang, S. W.,Wong, T. C.,Hui, A. J.,Chow, C. M.,Yu, H. H.,Li, M. F.,Ng, K. K.,Ching, J.,Wu, J. C.,Chan, F. K.,Sung, J. J. (2015). Environmental risk factors in inflammatory bowel disease: a population-based case-control study in Asia-Pacific Gut, 64(7), 1063-71 | Intervention/exposure
1859 | Ngale, K. M.,Santos, I. S.,Gonzalez-Chica, D. A.,de Barros, A. J.,Matijasevich, A. (2013). Bed-sharing and risk of hospitalisation due to pneumonia and diarrhoea in infancy: the 2004 Pelotas Birth Cohort J Epidemiol Community Health, 67(3), 245-9 | Outcome
1860 | Ngamphaiboon, J. (2014). Food allergy and wheezing Southeast Asian J Trop Med Public Health, 45 Suppl 1(#issue#), 95-9 | Study design
1861 | Ngamphaiboon, J.,Tansupapol, C.,Chatchatee, P. (2009). The efficacy of partially hydrolyzed formulas for allergy prevention in children under five years Asian Biomedicine, 3(3), 245-254 | Outcome
1862 | Nguyen, N. D.,Allen, J. R.,Peat, J. K.,Beal, P.,Webster, B. H.,Gaskin, K. J. (2004). Iron status of young Vietnamese children in Australia J Paediatr Child Health, 40(8), 424-9 | Study design, Intervention/exposure
1863 | Nguyen, N. D.,Allen, J. R.,Peat, J. K.,Schofield, W. N.,Nossar, V.,Eisenbruch, M.,Gaskin, K. J. (2004). Growth and feeding practices of Vietnamese infants in Australia Eur J Clin Nutr, 58(2), 356-62 | Intervention/exposure
1864 | Nicolai, A.,Nenna, R.,Stefanelli, P.,Carannante, A.,Schiavariello, C.,Pierangeli, A.,Scagnolari, C.,Moretti, C.,Papoff, P.,Bonci, E.,Ferrara, M.,Papasso, S.,Midulla, F. (2013). Bordetella pertussis in infants hospitalized for acute respiratory symptoms remains a concern BMC Infect Dis, 13(#issue#), 526 | Size of study groups, OUtcome
1865 | Nicoll, A.,Williams, A. (2002). Breast feeding Arch Dis Child, 87(2), 91-2 | Study design
1866 | Niegel, S.,Ystrom, E.,Hagtvet, K. A.,Vollrath, M. E. (2008). Difficult temperament, breastfeeding, and their mutual prospective effects: the Norwegian Mother and Child Cohort Study J Dev Behav Pediatr, 29(6), 458-62 | Intervention/exposure
1867 | Nielsen, G. A.,Thomsen, B. L.,Michaelsen, K. F. (1998). Influence of breastfeeding and complementary food on growth between 5 and 10 months Acta Paediatr, 87(9), 911-7 | Outcome
1868 | Nielsen, S. B.,Reilly, J. J.,Fewtrell, M. S.,Eaton, S.,Grinham, J.,Wells, J. C. (2011). Adequacy of milk intake during exclusive breastfeeding: a longitudinal study Pediatrics, 128(4), e907-14 | Outcome
1869 | Niemela, A.,Jarvenpaa, A. L. (1996). Is breastfeeding beneficial and maternal smoking harmful to the cognitive development of children? Acta Paediatr, 85(10), 1202-6 | Outcome
1870 | Niemela, M.,Uhari, M.,Mottonen, M. (1995). A pacifier increases the risk of recurrent acute otitis media in children in day care centers Pediatrics, 96(5 Pt 1), 884-8 | Outcome
1871 | Nikpour, S.,Rahimian, Sh,Shokrabi, S.,Haghani, H. (2012). Related Factors of Acute Leukemia in Children and the Role of Breast Feeding Iranian Journal of Endocrinology & Metabolism, 14(1), 63-97 35p | Language
1872 | Nishimura, M.,Oda, T.,Kariya, N.,Matsumura, S.,Shimono, T. (2008). Using a caries activity test to predict caries risk in early childhood J Am Dent Assoc, 139(1), 63-71 | Outcome
1873 | Nishimura, T.,Suzue, J.,Kaji, H. (2009). Breastfeeding reduces the severity of respiratory syncytial virus infection among young infants: a multi-center prospective study Pediatr Int, 51(6), 812-6 | Outcome
1874 | Nnanyelugo, D. O. (1982). Nutritional practices and food intake measurements and their relationship to socio-economic grouping, location and their apparent nutritional adequacy in children Appetite, 3(3), 229-41 | Country
1875 | Noda, M.,Sato, N.,Tanaka, T. (2015). Growth failure starts from early infancy in children with short stature at age 6 Clinical Pediatric Endocrinology, 24(1), 1-10 | Study design
1876 | Nolan, L.,Goel, V. (1995). Sociodemographic factors related to breastfeeding in Ontario: results from the Ontario Health Survey Can J Public Health, 86(5), 309-12 | Study design
1877 | Nommsen-Rivers, L. A. (2004). Does breastfeeding protect against infant mortality in the United States? J Hum Lact, 20(3), 357-8 | Study design
1878 | Nossar, V.,Hudson, D. (2001). Improving health outcomes for children by home visiting Medicine Today, 2(8), 135-136 | Study design
1879 | Nott, S. (1985). Some faults on feeding Midwife Health Visit Community Nurse, 21(6), 201-2 | Study design
1880 | Novotny, R.,Daida, Y. G.,Grove, J. S.,Acharya, S.,Vogt, T. M. (2003). Formula feeding in infancy is associated with adolescent body fat and earlier menarche Cell Mol Biol (Noisy-le-grand), 49(8), 1289-93 | Study design
1881 | Novotny, R.,Mata, L. J. (1983). Breast milk consumption in rural Costa Rica Arch Latinoam Nutr, 33(2), 377-86 | Size of study groups
1882 | Nuesslein, T. G.,Beckers, D.,Rieger, C. H. (1999). Cotinine in meconium indicates risk for early respiratory tract infections Hum Exp Toxicol, 18(4), 283-90 | Intervention/exposure
1883 | Nunes, A. M.,Alves, C. M.,Borba de Araujo, F.,Ortiz, T. M.,Ribeiro, M. R.,Silva, A. A.,Ribeiro, C. C. (2012). Association between prolonged breast-feeding and early childhood caries: a hierarchical approach Community Dent Oral Epidemiol, 40(6), 542-9 | Study design
1884 | Nwaru, B. I.,Craig, L. C.,Allan, K.,Prabhu, N.,Turner, S. W.,McNeill, G.,Erkkola, M.,Seaton, A.,Devereux, G. (2013). Breastfeeding and introduction of complementary foods during infancy in relation to the risk of asthma and atopic diseases up to 10 years Clin Exp Allergy, 43(11), 1263-73 | Outcome
1885 | Nwaru, B. I.,Erkkola, M.,Ahonen, S.,Kaila, M.,Haapala, A. M.,Kronberg-Kippila, C.,Salmelin, R.,Veijola, R.,Ilonen, J.,Simell, O.,Knip, M.,Virtanen, S. M. (2010). Age at the introduction of solid foods during the first year and allergic sensitization at age 5 years Pediatrics, 125(1), 50-9 | Outcome
1886 | Nwaru, B. I.,Takkinen, H. M.,Niemela, O.,Kaila, M.,Erkkola, M.,Ahonen, S.,Haapala, A. M.,Kenward, M. G.,Pekkanen, J.,Lahesmaa, R.,Kere, J.,Simell, O.,Veijola, R.,Ilonen, J.,Hyoty, H.,Knip, M.,Virtanen, S. M. (2013). Timing of infant feeding in relation to childhood asthma and allergic diseases J Allergy Clin Immunol, 131(1), 78-86 | Outcome
1887 | Nwaru, B. I.,Takkinen, H. M.,Niemela, O.,Kaila, M.,Erkkola, M.,Ahonen, S.,Tuomi, H.,Haapala, A. M.,Kenward, M. G.,Pekkanen, J.,Lahesmaa, R.,Kere, J.,Simell, O.,Veijola, R.,Ilonen, J.,Hyoty, H.,Knip, M.,Virtanen, S. M. (2013). Introduction of complementary foods in infancy and atopic sensitization at the age of 5 years: timing and food diversity in a Finnish birth cohort Allergy, 68(4), 507-16 | Outcome
1888 | Nylander, G.,Lindemann, R.,Helsing, E.,Bendvold, E. (1991). Unsupplemented breastfeeding in the maternity ward. Positive long-term effects Acta Obstet Gynecol Scand, 70(3), 205-9 | Study design, Intervention/exposure
1889 | Obel, C.,Henriksen, T. B.,Hedegaard, M.,Secher, N. J.,Ostergaard, J. (1998). Smoking during pregnancy and babbling abilities of the 8-month-old infant Paediatr Perinat Epidemiol, 12(1), 37-48 | Intervention/exposure
1890 | Ochoa, M. C.,Moreno-Aliaga, M. J.,Martinez-Gonzalez, M. A.,Martinez, J. A.,Marti, A. (2007). Predictor factors for childhood obesity in a Spanish case-control study Nutrition, 23(5), 379-84 | Study design
1891 | O’Connell, J. M.,Dibley, M. J.,Sierra, J.,Wallace, B.,Marks, J. S.,Yip, R. (1989). Growth of vegetarian children: The Farm Study Pediatrics, 84(3), 475-81 | Intervention/exposure
1892 | O’Connor, P. A. (1980). Clouds, skin color, and rickets Pediatrics, 66(2), 332 | Study design
1893 | Oddy, W. H. (2000). Breastfeeding and asthma in children. A prospective cohort study Adv Exp Med Biol, 478(#issue#), 393-4 | Publication status
1894 | Oddy, W. H. (2000). Breastfeeding and asthma in children: findings from a West Australian study Breastfeed Rev, 8(1), 5-11 | Redundant data with another article
1895 | Oddy, W. H.,de Klerk, N. H.,Sly, P. D.,Holt, P. G. (2002). The effects of respiratory infections, atopy, and breastfeeding on childhood asthma Eur Respir J, 19(5), 899-905 | Outcome
1896 | Oddy, W. H.,Halonen, M.,Martinez, F. D.,Lohman, I. C.,Stern, D. A.,Kurzius-Spencer, M.,Guerra, S.,Wright, A. L. (2003). TGF-beta in human milk is associated with wheeze in infancy J Allergy Clin Immunol, 112(4), 723-8 | Outcome
1897 | Oddy, W. H.,Holt, P. G.,Sly, P. D.,Read, A. W.,Landau, L. I.,Stanley, F. J.,Kendall, G. E.,Burton, P. R. (1999). Association between breast feeding and asthma in 6 year old children: findings of a prospective birth cohort study BMJ, 319(7213), 815-9 | Outcome
1898 | Oddy, W. H.,Kendall, G. E.,Blair, E.,de Klerk, N. H.,Silburn, S.,Zubrick, S. (2004). Breastfeeding and cognitive development in children Adv Exp Med Biol, 554(#issue#), 365-9 | Outcome
1899 | Oddy, W. H.,Kendall, G. E.,Blair, E.,De Klerk, N. H.,Stanley, F. J.,Landau, L. I.,Silburn, S.,Zubrick, S. (2003). Breast feeding and cognitive development in childhood: a prospective birth cohort study Paediatr Perinat Epidemiol, 17(1), 81-90 | Outcome
1900 | Oddy, W. H.,Kendall, G. E.,Li, J.,Jacoby, P.,Robinson, M.,de Klerk, N. H.,Silburn, S. R.,Zubrick, S. R.,Landau, L. I.,Stanley, F. J. (2010). The long-term effects of breastfeeding on child and adolescent mental health: a pregnancy cohort study followed for 14 years J Pediatr, 156(4), 568-74 | Outcome
1901 | Oddy, W. H.,Kickett-Tucker, C.,De Maio, J.,Lawrence, D.,Cox, A.,Silburn, S. R.,Stanley, F. J.,Zubrick, S. R. (2008). The association of infant feeding with parent-reported infections and hospitalisations in the West Australian Aboriginal Child Health Survey Aust N Z J Public Health, 32(3), 207-15 | Outcome
1902 | Oddy, W. H.,Li, J.,Whitehouse, A. J. O.,Zubrick, S. R.,Malacova, E. (2011). Breastfeeding duration and academic achievement at 10 years Pediatrics, 127(1), e137-e145 | Outcome
1903 | Oddy, W. H.,Mori, T. A.,Huang, R. C.,Marsh, J. A.,Pennell, C. E.,Chivers, P. T.,Hands, B. P.,Jacoby, P.,Rzehak, P.,Koletzko, B. V.,Beilin, L. J. (2014). Early infant feeding and adiposity risk: From infancy to adulthood Annals of Nutrition and Metabolism, 64(3-4), 262-270 | Redundant data with another study
1904 | Oddy, W. H.,Peat, J. K.,de Klerk, N. H. (2002). Maternal asthma, infant feeding, and the risk of asthma in childhood J Allergy Clin Immunol, 110(1), 65-7 | Intervention/exposure
1905 | Oddy, W. H.,Robinson, M.,Kendall, G. E.,Li, J.,Zubrick, S. R.,Stanley, F. J. (2011). Breastfeeding and early child development: a prospective cohort study Acta Paediatr, 100(7), 992-9 | Outcome
1906 | Oddy, W. H.,Scott, J. A.,Graham, K. I.,Binns, C. W. (2006). Breastfeeding influences on growth and health at one year of age Breastfeed Rev, 14(1), 15-23 | Outcome
1907 | Oddy, W. H.,Sherriff, J. L.,de Klerk, N. H.,Kendall, G. E.,Sly, P. D.,Beilin, L. J.,Blake, K. B.,Landau, L. I.,Stanley, F. J. (2004). The relation of breastfeeding and body mass index to asthma and atopy in children: a prospective cohort study to age 6 years Am J Public Health, 94(9), 1531-7 | Outcome
1908 | Oddy, W. H.,Sly, P. D.,de Klerk, N. H.,Landau, L. I.,Kendall, G. E.,Holt, P. G.,Stanley, F. J. (2003). Breast feeding and respiratory morbidity in infancy: a birth cohort study Arch Dis Child, 88(3), 224-8 | Outcome
1909 | Oddy, W. H.,Smith, G. J.,Jacoby, P. (2014). A possible strategy for developing a model to account for attrition bias in a longitudinal cohort to investigate associations between exclusive breastfeeding and overweight and obesity at 20 years Ann Nutr Metab, 65(2-3), 234-5 | Study design, Intervention/exposure
1910 | Odelram, H.,Vanto, T.,Jacobsen, L.,Kjellman, N. I. (1996). Whey hydrolysate compared with cow’s milk-based formula for weaning at about 6 months of age in high allergy-risk infants: effects on atopic disease and sensitization Allergy, 51(3), 192-5 | Intervention/exposure
1911 | O’Donovan, S. M.,O’B Hourihane J,Murray, D. M.,Kenny, L. C.,Khashan, A. S.,Chaoimh, C. N.,Irvine, A. D.,Kiely, M. (2015). Neonatal adiposity increases the risk of atopic dermatitis during the first year of life J Allergy Clin Immunol, #volume#(#issue#), #Pages# | Intervention/exposure
1912 | Ogawa, K.,Ben, R. A.,Pons, S.,de Paolo, M. I.,Bustos Fernandez, L. (1992). Volatile fatty acids, lactic acid, and pH in the stools of breast-fed and bottle-fed infants J Pediatr Gastroenterol Nutr, 15(3), 248-52 | Size of study groups, Outcome
1913 | Ogston, S. A.,Florey, C. D.,Walker, C. H. (1987). Association of infant alimentary and respiratory illness with parental smoking and other environmental factors J Epidemiol Community Health, 41(1), 21-5 | Outcome
1914 | Ohlund, I.,Hornell, A.,Lind, T.,Hernell, O. (2008). Dietary fat in infancy should be more focused on quality than on quantity Eur J Clin Nutr, 62(9), 1058-64 | Outcome
1915 | Oken, E.,Osterdal, M. L.,Gillman, M. W.,Knudsen, V. K.,Halldorsson, T. I.,Strom, M.,Bellinger, D. C.,Hadders-Algra, M.,Michaelsen, K. F.,Olsen, S. F. (2008). Associations of maternal fish intake during pregnancy and breastfeeding duration with attainment of developmental milestones in early childhood: a study from the Danish National Birth Cohort Am J Clin Nutr, 88(3), 789-96 | Outcome
1916 | Olaya, G. A.,Lawson, M.,Fewtrell, M. S. (2013). Efficacy and safety of new complementary feeding guidelines with an emphasis on red meat consumption: a randomized trial in Bogota, Colombia Am J Clin Nutr, 98(4), 983-93 | Intervention/exposure
1917 | Oliveira, A. F.,Chaves, A. M.,Rosenblatt, A. (2006). The influence of enamel defects on the development of early childhood caries in a population with low socioeconomic status: a longitudinal study Caries Res, 40(4), 296-302 | Intervention/exposure
1918 | Oliveira, E. A.,Bertoldi, A. D.,Domingues, M. R.,Santos, I. S.,Barros, A. J. (2012). Factors associated to medicine use among children from the 2004 Pelotas Birth Cohort (Brazil) Rev Saude Publica, 46(3), 487-96 | Outcome
1919 | Ollila, P.,Larmas, M. (2007). A seven-year survival analysis of caries onset in primary second molars and permanent first molars in different caries risk groups determined at age two years Acta Odontol Scand, 65(1), 29-35 | Outcome
1920 | Ölmez, S.,Uzamiş, M. (2002). Risk factors of early childhood caries in Turkish children Turkish Journal of Pediatrics, 44(3), 230-236 | Study design
1921 | Olmez, S.,Uzamis, M.,Erdem, G. (2003). Association between early childhood caries and clinical, microbiological, oral hygiene and dietary variables in rural Turkish children Turk J Pediatr, 45(3), 231-6 | Study design
1922 | Olson, C. M.,Baker, I. R.,Demment, M. M.,Graham, M. L.,May, J. J.,Strawderman, M. S.,Wells, N. M. (2014). The healthy start partnership: an approach to obesity prevention in young families Fam Community Health, 37(1), 74-85 | Intervention/exposure
1923 | Ong, K. K.,Ahmed, M. L.,Sherriff, A.,Woods, K. A.,Watts, A.,Golding, J.,Dunger, D. B. (1999). Cord blood leptin is associated with size at birth and predicts infancy weight gain in humans. ALSPAC Study Team. Avon Longitudinal Study of Pregnancy and Childhood J Clin Endocrinol Metab, 84(3), 1145-8 | Intervention/exposure
1924 | Ong, K. K.,Emmett, P. M.,Noble, S.,Ness, A.,Dunger, D. B. (2006). Dietary energy intake at the age of 4 months predicts postnatal weight gain and childhood body mass index Pediatrics, 117(3), e503-8 | Intervention/exposure
1925 | Ong, K. K.,Preece, M. A.,Emmett, P. M.,Ahmed, M. L.,Dunger, D. B. (2002). Size at birth and early childhood growth in relation to maternal smoking, parity and infant breast-feeding: longitudinal birth cohort study and analysis Pediatr Res, 52(6), 863-7 | Outcome
1926 | Oppitz, I. N.,Cesar, J. A.,Neumann, N. A. (2014). Overweight among children under five years of age in municipalities of the semiarid region Rev Bras Epidemiol, 17(4), 860-72 | Study design
1927 | Orakzai, S. A.,Siddiqui, K. A.,Ayub, M.,Saeed, A. K. (1987). Serum proteins in infants J Pak Med Assoc, 37(10), 251-5 | Study design
1928 | Orivuori, L.,Loss, G.,Roduit, C.,Dalphin, J. C.,Depner, M.,Genuneit, J.,Lauener, R.,Pekkanen, J.,Pfefferle, P.,Riedler, J.,Roponen, M.,Weber, J.,von Mutius, E.,Braun-Fahrlander, C.,Vaarala, O. (2014). Soluble immunoglobulin A in breast milk is inversely associated with atopic dermatitis at early age: the PASTURE cohort study Clin Exp Allergy, 44(1), 102-12 | Outcome
1929 | Orozco, A. C.,Munoz, A. M.,Velasquez, C. M.,Uscategui, R. M.,Parra, M. V.,Patino, F. A.,Manjarres, L. M.,Parra, B. E.,Estrada, A.,Agudelo, G. M. (2014). Variant in CAPN10 gene and environmental factors show evidence of association with excess weight among young people in a Colombian population Biomedica, 34(4), 546-55 | Study design
1930 | Orr P,McDonald S,Milley D,Brown R (2001). Bronchiolitis in Inuit children from a Canadian central arctic community, 1995-1996 Int J Circumpolar Health, 60(#issue#), 649-58 | Outcome
1931 | Ortega-Garcia, J. A.,Ferris-Tortajada, J.,Torres-Cantero, A. M.,Soldin, O. P.,Torres, E. P.,Fuster-Soler, J. L.,Lopez-Ibor, B.,Madero-Lopez, L. (2008). Full breastfeeding and paediatric cancer J Paediatr Child Health, 44(1-2), 10-3 | Outcome
1932 | O’Ryan, M. L.,Lucero, Y.,Rabello, M.,Mamani, N.,Salinas, A. M.,Pena, A.,Torres-Torreti, J. P.,Mejias, A.,Ramilo, O.,Suarez, N.,Reynolds, H. E.,Orellana, A.,Lagomarcino, A. J. (2015). Persistent and transient Helicobacter pylori infections in early childhood Clin Infect Dis, 61(2), 211-8 | Outcome
1933 | Ostrom, K. M.,Cordle, C. T.,Schaller, J. P.,Winship, T. R.,Thomas, D. J.,Jacobs, J. R.,Blatter, M. M.,Cho, S.,Gooch, W. M., 3rd,Granoff, D. M.,Faden, H.,Pickering, L. K. (2002). Immune status of infants fed soy-based formulas with or without added nucleotides for 1 year: part 1: vaccine responses, and morbidity J Pediatr Gastroenterol Nutr, 34(2), 137-44 | Outcome
1934 | O’Sullivan, D. M.,Tinanoff, N. (1993). Social and biological factors contributing to caries of the maxillary anterior teeth Pediatr Dent, 15(1), 41-4 | Study design
1935 | Oti-Boateng, P.,Seshadri, R.,Petrick, S.,Gibson, R. A.,Simmer, K. (1998). Iron status and dietary iron intake of 6-24-month-old children in Adelaide J Paediatr Child Health, 34(3), 250-3 | Study design
1936 | O’Tierney, P. F.,Barker, D. J.,Osmond, C.,Kajantie, E.,Eriksson, J. G. (2009). Duration of breast-feeding and adiposity in adult life J Nutr, 139(2), 422S-5S | Outcome
1937 | Ou X,Andres A,Pivik RT,Cleves MA,Snow JH,Ding Z,Badger TM (2015). Voxel-Based Morphometry and fMRI Revealed Differences in Brain Gray Matter in Breastfed and Milk Formula-Fed Children AJNR Am J Neuroradiol, #volume#(#issue#), #Pages# | Study design, Outcome
1938 | Ou, X.,Andres, A.,Cleves, M. A.,Pivik, R. T.,Snow, J. H.,Ding, Z.,Badger, T. M. (2014). Sex-specific association between infant diet and white matter integrity in 8-y-old children Pediatr Res, 76(6), 535-43 | Outcome, Size of study groups
1939 | Oulis, C. J.,Berdouses, E. D.,Vadiakas, G.,Lygidakis, N. A. (1999). Feeding practices of Greek children with and without nursing caries Pediatr Dent, 21(7), 409-16 | Study design, Size of study groups
1940 | Ounsted, M. K.,Moar, V. A.,Scott, A. (1983). Small-for-dates babies at the age of four years: health, handicap and developmental status Early Hum Dev, 8(3-4), 243-58 | Intervention/exposure
1941 | Ounsted, M.,Moar, V. A.,Cockburn, J.,Redman, C. W. (1984). Factors associated with the intellectual ability of children born to women with high risk pregnancies Br Med J (Clin Res Ed), 288(6423), 1038-41 | Size of study groups
1942 | Ovsenik, M. (2009). Incorrect orofacial functions until 5 years of age and their association with posterior crossbite Am J Orthod Dentofacial Orthop, 136(3), 375-81 | Study design, Intervention/exposure
1943 | Owen, G. M.,Garry, P. J.,Hooper, E. M.,Gilbert, B. A.,Pathak, D. (1981). Iron nutriture of infants exclusively breast-fed the first five months J Pediatr, 99(2), 237-40 | Intervention/exposure
1944 | Owen, M. J.,Baldwin, C. D.,Swank, P. R.,Pannu, A. K.,Johnson, D. L.,Howie, V. M. (1993). Relation of infant feeding practices, cigarette smoke exposure, and group child care to the onset and duration of otitis media with effusion in the first two years of life J Pediatr, 123(5), 702-11 | Outcome
1945 | Ozden, T. A.,Gokcay, G.,Cantez, M. S.,Durmaz, O.,Issever, H.,Omer, B.,Saner, G. (2015). Copper, zinc and iron levels in infants and their mothers during the first year of life: a prospective study BMC Pediatr, 15(1), 157 | Study design, Intervention/exposure
1946 | Ozmert, E. N.,Kale-Cekinmez, E.,Yurdakok, K.,Sekerel, B. E. (2009). Determinants of allergic signs and symptoms in 24- 48-month-old Turkish children Turk J Pediatr, 51(2), 103-9 | Study design, Size of study groups
1947 | Ozmert, E. N.,Yurdakok, K.,Soysal, S.,Kulak-Kayikci, M. E.,Belgin, E.,Ozmert, E.,Laleli, Y.,Saracbasi, O. (2005). Relationship between physical, environmental and sociodemographic factors and school performance in primary schoolchildren J Trop Pediatr, 51(1), 25-32 | Study design
1948 | Pacheco, G.,Hedges, M.,Schilling, C.,Morton, S. (2013). Pre- and postnatal drivers of childhood intelligence: evidence from Singapore J Biosoc Sci, 45(1), 41-56 | Study design
1949 | Paine, B. J.,Makrides, M.,Gibson, R. A. (1999). Duration of breast-feeding and Bayley’s Mental Developmental Index at 1 year of age J Paediatr Child Health, 35(1), 82-5 | Study design
1950 | Paine, R.,Coble, R. J. (1982). Breast-feeding and infant health in a rural US community Am J Dis Child, 136(1), 36-8 | Size of study groups, Intervention/exposure
1951 | Palloni, A.,Aguirre, G. P.,Lastiri, S. (1994). The effects of breast-feeding and the pace of childbearing on early childhood mortality in Mexico Bull Pan Am Health Organ, 28(2), 93-111 | Study design, Intervention/exposure
1952 | Palloni, A.,Tienda, M. (1986). The effects of breastfeeding and pace of childbearing on mortality at early ages Demography, 23(1), 31-52 | Study design
1953 | Palma, G. D.,Capilla, A.,Nova, E.,Castillejo, G.,Varea, V.,Pozo, T.,Garrote, J. A.,Polanco, I.,Lopez, A.,Ribes-Koninckx, C.,Marcos, A.,Garcia-Novo, M. D.,Calvo, C.,Ortigosa, L.,Pena-Quintana, L.,Palau, F.,Sanz, Y. (2012). Influence of milk-feeding type and genetic risk of developing coeliac disease on intestinal microbiota of infants: the PROFICEL study PLoS One, 7(2), e30791 | Outcome
1954 | Palmer, M. M.,VandenBerg, K. A. (1998). A closer look at neonatal sucking Neonatal Netw, 17(2), 77-9 | Study design
1955 | Palti, H.,Mansbach, I.,Pridan, H.,Adler, B.,Palti, Z. (1984). Episodes of illness in breast-fed and bottle-fed infants in Jerusalem Isr J Med Sci, 20(5), 395-9 | Intervention/exposure
1956 | Palvo, F.,Toledo, E. C.,Menin, A. M.,Jorge, P. P.,Godoy, M. F.,Sole, D. (2008). Risk factors of childhood asthma in Sao Jose do Rio Preto, Sao Paulo, Brazil J Trop Pediatr, 54(4), 253-7 | Study design
1957 | Panagiotakos, D. B.,Papadimitriou, A.,Anthracopoulos, M. B.,Konstantinidou, M.,Antonogeorgos, G.,Fretzayas, A.,Priftis, K. N. (2008). Birthweight, breast-feeding, parental weight and prevalence of obesity in schoolchildren aged 10-12 years, in Greece; the Physical Activity, Nutrition and Allergies in Children Examined in Athens (PANACEA) study Pediatr Int, 50(4), 563-8 | Study design
1958 | Panico, L.,Stuart, B.,Bartley, M.,Kelly, Y. (2014). Asthma trajectories in early childhood: identifying modifiable factors PLoS One, 9(11), e111922 | Outcome
1959 | Papandreou, D.,Malindretos, P.,Rousso, I. (2010). Risk factors for childhood obesity in a Greek paediatric population Public Health Nutr, 13(10), 1535-9 | Study design, Size of study groups
1960 | Papenburg, J.,Hamelin, M. E.,Ouhoummane, N.,Carbonneau, J.,Ouakki, M.,Raymond, F.,Robitaille, L.,Corbeil, J.,Caouette, G.,Frenette, L.,De Serres, G.,Boivin, G. (2012). Comparison of risk factors for human metapneumovirus and respiratory syncytial virus disease severity in young children J Infect Dis, 206(2), 178-89 | Participant health
1961 | Papp, L. M. (2014). Longitudinal associations between breastfeeding and observed mother-child interaction qualities in early childhood Child Care Health Dev, 40(5), 740-6 | Outcome
1962 | Paradise, J. L.,Rockette, H. E.,Colborn, D. K.,Bernard, B. S.,Smith, C. G.,Kurs-Lasky, M.,Janosky, J. E. (1997). Otitis media in 2253 Pittsburgh-area infants: prevalence and risk factors during the first two years of life Pediatrics, 99(3), 318-33 | Outcome
1963 | Parazzini, F.,Cipriani, S.,Zinetti, C.,Chatenoud, L.,Frigerio, L.,Amuso, G.,Ciammella, M.,Di Landro, A.,Naldi, L. (2014). Perinatal factors and the risk of atopic dermatitis: a cohort study Pediatr Allergy Immunol, 25(1), 43-50 | Outcome
1964 | Paricio Talayero JM,Lizan-Garcia M,Otero Puime A,Benlloch Muncharaz MJ,Beseler Soto B,Sanchez-Palomares M,Santos Serrano L,Rivera LL (2006). Full breastfeeding and hospitalization as a result of infections in the first year of life Pediatrics, 118(#issue#), e92-9 | Intervention/exposure
1965 | Park, J.,Kim, H. S.,Chu, S. H.,Jekal, Y. S.,Lee, J. Y. (2015). The effect of predominant breast-feeding on the risk of obesity in Korean preschool children Nurs Health Sci, #volume#(#issue#), #Pages# | Study design
1966 | Park, M. J.,Namgung, R.,Kim, D. H.,Tsang, R. C. (1998). Bone mineral content is not reduced despite low vitamin D status in breast milk-fed infants versus cow’s milk based formula-fed infants J Pediatr, 132(4), 641-5 | Size of study groups
1967 | Park, S.,Kim, B. N.,Kim, J. W.,Shin, M. S.,Yoo, H. J.,Cho, S. C. (2014). Protective effect of breastfeeding with regard to children’s behavioral and cognitive problems Nutr J, 13(1), 111 | Study design
1968 | Parra-Cabrera, S.,Moreno-Macias, H.,Mendez-Ramirez, I.,Schnaas, L.,Romieu, I. (2008). Maternal dietary omega fatty acid intake and auditory brainstem-evoked potentials in Mexican infants born at term: Cluster analysis Early Human Development, 84(1), 51-57 | Intervention/exposure
1969 | Parsons, T. J.,Power, C.,Manor, O. (2003). Infant feeding and obesity through the lifecourse Arch Dis Child, 88(9), 793-4 | Outcome
1970 | Paszkowski, J.,Lopatynski, J. (2002). Allergy to house dust mites in primary health care subjects with chronic or recurrent inflammatory states of respiratory system Ann Univ Mariae Curie Sklodowska Med, 57(1), 522-30 | Participant health
1971 | Patel, J. A.,Alvarez-Fernandez, P.,Jennings, K.,Loeffelholz, M.,McCormick, D.,Chonmaitree, T. (2015). Factors Affecting Staphylococcus aureus Colonization of the Nasopharynx in the First 6 Months of Life Pediatr Infect Dis J, 34(8), 826-30 | Outcome
1972 | Patel, J. A.,Nair, S.,Revai, K.,Grady, J.,Saeed, K.,Matalon, R.,Block, S.,Chonmaitree, T. (2006). Association of proinflammatory cytokine gene polymorphisms with susceptibility to otitis media Pediatrics, 118(6), 2273-9 | Study design, Outcome
1973 | Paterson, J. E.,Gao, W.,Sundborn, G.,Cartwright, S. (2011). Maternal self-report of oral health in six-year-old Pacific children from South Auckland, New Zealand Community Dent Oral Epidemiol, 39(1), 19-28 | Outcome
1974 | Paterson, J.,Iusitini, L.,Gao, W. (2011). Child developmental assessment at two-years of age: data from the Pacific Islands Families Study Pac Health Dialog, 17(2), 51-63 | Outcome
1975 | Patra, S.,Singh, V.,Kumar, P.,Chandra, J.,Dutta, A.,Tripathi, M. (2011). Demographic and clinical profile of children under two years of age with recurrent wheezing J Coll Physicians Surg Pak, 21(11), 715-7 | Country, Size of study group
1976 | Patsourou, A.,Konstantinides, T.,Mantadakis, E.,Tsalkidis, A.,Zarras, C.,Balaska, A.,Simopoulos, K.,Chatzimichael, A. (2012). Growth of exclusively breastfed and self-weaned children of Greece aged 0-36 months Breastfeed Med, 7(6), 521-5 | Study design
1977 | Patterson, C. C.,Carson, D. J.,Hadden, D. R.,Waugh, N. R.,Cole, S. K. (1994). A case-control investigation of perinatal risk factors for childhood IDDM in Northern Ireland and Scotland Diabetes Care, 17(5), 376-81 | Intervention/exposure
1978 | Patwari, A. K. (1996). Breastfeeding and atopy Indian Pediatr, 33(3), 265-6 | Country, Study design
1979 | Paul A,Whitehead R (1986). Infant feeding: the weighting game Community Outlook, #volume#(#issue#), 11-7 | Study design
1980 | Paul, K.,Dittrichova, J.,Papousek, H. (1996). Infant feeding behavior: development in patterns and motivation Dev Psychobiol, 29(7), 563-76 | Size of study groups
1981 | Pavic, I.,Jurkovic, M.,Pastar, Z. (2012). Risk factors for acute respiratory tract infections in children Coll Antropol, 36(2), 539-42 | Study design
1982 | Pearce, M. S.,Birrell, F. N.,Francis, R. M.,Rawlings, D. J.,Tuck, S. P.,Parker, L. (2005). Lifecourse study of bone health at age 49-51 years: the Newcastle thousand families cohort study J Epidemiol Community Health, 59(6), 475-80 | Intervention/exposure
1983 | Pearce, M. S.,Relton, C. L.,Parker, L.,Unwin, N. C. (2009). Sex differences in the association between infant feeding and blood cholesterol in later life: the Newcastle thousand families cohort study at age 49-51 years Eur J Epidemiol, 24(7), 375-80 | Outcome
1984 | Pearce, M. S.,Unwin, N. C.,Parker, L.,Alberti, K. G. (2006). Life course determinants of insulin secretion and sensitivity at age 50 years: the Newcastle thousand families study Diabetes Metab Res Rev, 22(2), 118-25 | Outcome
1985 | Pearson, Catherine (2013). Study Finds Breastfeeding May Lower Alzheimer’s Risk Inside Childbirth Education, #volume#(#issue#), 9-9 1p | Study design
1986 | Peat, J. K. (1998). Can asthma be prevented? Evidence from epidemiological studies of children in Australia and New Zealand in the last decade Clin Exp Allergy, 28(3), 261-5 | Study design
1987 | Peat, J. K.,Allen, J.,Oddy, W.,Webb, K. (2003). Breastfeeding and asthma: appraising the controversy Pediatr Pulmonol, 35(5), 331-4 | Study design
1988 | Pedersen, C. B.,Zachau-Christiansen, B. (1986). Otitis media in Greenland children: acute, chronic and secretory otitis media in three- to eight-year-olds J Otolaryngol, 15(6), 332-5 | Study design
1989 | Pehlivan, I.,Hatun, Ş,Aydoǧan, M.,Babaoǧlu, K.,Gökalp, S. A. (2003). Maternal vitamin D defiency and vitamin D supplementation in healthy infants Turkish Journal of Pediatrics, 45(4), 315-320 | Intervention/exposure
1990 | Pei, Z.,Heinrich, J.,Fuertes, E.,Flexeder, C.,Hoffmann, B.,Lehmann, I.,Schaaf, B.,von Berg, A.,Koletzko, S. (2014). Cesarean delivery and risk of childhood obesity J Pediatr, 164(5), 1068-1073 e2 | Intervention/exposure
1991 | Pelayo, L.,Nunez, F. A.,Rojas, L.,Wilke, H.,Furuseth Hansen, E.,Mulder, B.,Gjerde, B.,Robertson, L. (2008). Molecular and epidemiological investigations of cryptosporidiosis in Cuban children Ann Trop Med Parasitol, 102(8), 659-69 | Participant health, Size of study groups
1992 | Peltzer, K.,Mongkolchati, A.,Satchaiyan, G.,Rajchagool, S.,Pimpak, T. (2014). Sociobehavioral factors associated with caries increment: a longitudinal study from 24 to 36 months old children in Thailand Int J Environ Res Public Health, 11(10), 10838-50 | Outcome
1993 | Penders, J.,Gerhold, K.,Stobberingh, E. E.,Thijs, C.,Zimmermann, K.,Lau, S.,Hamelmann, E. (2013). Establishment of the intestinal microbiota and its role for atopic dermatitis in early childhood J Allergy Clin Immunol, 132(3), 601-607 e8 | Intervention/exposure, Outcome
1994 | Peneau, S.,Hercberg, S.,Rolland-Cachera, M. F. (2014). Breastfeeding, early nutrition, and adult body fat J Pediatr, 164(6), 1363-8 | Size of study groups
1995 | Penn, A. H.,Carver, L. J.,Herbert, C. A.,Lai, T. S.,McIntire, M. J.,Howard, J. T.,Taylor, S. F.,Schmid-Schonbein, G. W.,Dobkins, K. R. (2016). Breast Milk Protects Against Gastrointestinal Symptoms in Infants at High Risk for Autism During Early Development J Pediatr Gastroenterol Nutr, 62(2), 317-27 | Outcome
1996 | Penwell, A. (2012). Breastfeeding and newborn survival Midwifery Today Int Midwife, #volume#(101), 51-3 | Study design
1997 | Perera, B. J. (2010). Preventive strategies for acute respiratory infections in children Ceylon Med J, 55(4), 103-5 | Study design
1998 | Perera, B. J.,Ganesan, S.,Jayarasa, J.,Ranaweera, S. (1999). The impact of breastfeeding practices on respiratory and diarrhoeal disease in infancy: a study from Sri Lanka J Trop Pediatr, 45(2), 115-8 | Study design, Outcome
1999 | Peres, K. G.,Cascaes, A. M.,Peres, M. A.,Demarco, F. F.,Santos, I. S.,Matijasevich, A.,Barros, A. J. (2015). Exclusive Breastfeeding and Risk of Dental Malocclusion Pediatrics, 136(1), e60-7 | Outcome
2000 | Perez-Bravo, F.,Carrasco, E.,Gutierrez-Lopez, M. D.,Martinez, M. T.,Lopez, G.,de los Rios, M. G. (1996). Genetic predisposition and environmental factors leading to the development of insulin-dependent diabetes mellitus in Chilean children J Mol Med (Berl), 74(2), 105-9 | Outcome
2001 | Perez-Bravo, F.,Oyarzun, A.,Carrasco, E.,Albala, C.,Dorman, J. S.,Santos, J. L. (2003). Duration of breast feeding and bovine serum albumin antibody levels in type 1 diabetes: a case-control study Pediatr Diabetes, 4(4), 157-61 | Outcome
2002 | Peroni, D. G.,Piacentini, G. L.,Alfonsi, L.,Zerman, L.,Di Blasi, P.,Visona, G.,Nottegar, F.,Boner, A. L. (2003). Rhinitis in pre-school children: prevalence, association with allergic diseases and risk factors Clin Exp Allergy, 33(10), 1349-54 | Study design
2003 | Perrillat, F.,Clavel, J.,Auclerc, M. F.,Baruchel, A.,Leverger, G.,Nelken, B.,Philippe, N.,Schaison, G.,Sommelet, D.,Vilmer, E.,Hemon, D. (2002). Day-care, early common infections and childhood acute leukaemia: a multicentre French case-control study Br J Cancer, 86(7), 1064-9 | Outcome
2004 | Perrillat, F.,Clavel, J.,Jaussent, I.,Baruchel, A.,Leverger, G.,Nelken, B.,Philippe, N.,Schaison, G.,Sommelet, D.,Vilmer, E.,Hémon, D. (2002). Breast-feeding, fetal loss and childhood acute leukaemia European Journal of Pediatrics, 161(4), 235-237 | Outcome
2005 | Perrine, C. G.,Sharma, A. J.,Jefferds, M. E.,Serdula, M. K.,Scanlon, K. S. (2010). Adherence to vitamin D recommendations among US infants Pediatrics, 125(4), 627-32 | Study design
2006 | Persico, M.,Podoshin, L.,Fradis, M.,Golan, D.,Wellisch, G. (1983). Recurrent middle-ear infections in infants: the protective role of maternal breast feeding Ear Nose Throat J, 62(6), 297-304 | Participant health, Outcomes
2007 | Persson, L. A. (1985). Infant feeding and growth--a longitudinal study in three Swedish communities Ann Hum Biol, 12(1), 41-52 | Outcome
2008 | Persson, L. A.,Lundstrom, M.,Lonnerdal, B.,Hernell, O. (1998). Are weaning foods causing impaired iron and zinc status in 1-year-old Swedish infants? A cohort study Acta Paediatr, 87(6), 618-22 | Intervention/exposure
2009 | Perumal, N.,Al Mahmud, A.,Baqui, A. H.,Roth, D. E. (2015). Prenatal vitamin D supplementation and infant vitamin D status in Bangladesh Public Health Nutr, #volume#(#issue#), 1-9 | Country
2010 | Pesonen, M.,Kallio, M. J.,Ranki, A.,Siimes, M. A. (2006). Prolonged exclusive breastfeeding is associated with increased atopic dermatitis: a prospective follow-up study of unselected healthy newborns from birth to age 20 years Clin Exp Allergy, 36(8), 1011-8 | Intervention/exposure
2011 | Peters, D. C.,Worthington-Roberts, B. (1982). Infant feeding practices of middle-class breastfeeding and formula-feeding mothers Birth, 9(2), 91-5 | Outcome
2012 | Peters, K. E.,Huang, J.,Vaughn, M. G.,Witko, C. (2013). Does breastfeeding contribute to the racial gap in reading and math test scores? Ann Epidemiol, 23(10), 646-51 | Outcome
2013 | Peters, T. J.,Golding, J. (1987). The epidemiology of childhood eczema: II. Statistical analyses to identify independent early predictors Paediatr Perinat Epidemiol, 1(1), 80-94 | Intervention/exposure
2014 | Peters, U.,Schneeweiss, S.,Trautwein, E. A.,Erbersdobler, H. F. (2001). A case-control study of the effect of infant feeding on celiac disease Ann Nutr Metab, 45(4), 135-42 | Outcome
2015 | Petherick, A. (2010). Development: Mother’s milk: A rich opportunity Nature, 468(7327), S5-7 | Study design
2016 | Petridou, E.,Trichopoulos, D.,Kalapothaki, V.,Pourtsidis, A.,Kogevinas, M.,Kalmanti, M.,Koliouskas, D.,Kosmidis, H.,Panagiotou, J. P.,Piperopoulou, F.,Tzortzatou, F. (1997). The risk profile of childhood leukaemia in Greece: a nationwide case-control study Br J Cancer, 76(9), 1241-7 | Outcome
2017 | Petti, S.,Cairella, G.,Tarsitani, G. (2000). Rampant early childhood dental decay: an example from Italy J Public Health Dent, 60(3), 159-66 | Study design
2018 | Pettitt, D. J.,Forman, M. R.,Hanson, R. L.,Knowler, W. C.,Bennett, P. H. (1997). Breastfeeding and incidence of non-insulin-dependent diabetes mellitus in Pima Indians Lancet, 350(9072), 166-8 | Intervention/exposure, Outcome
2019 | Pettitt, D. J.,Knowler, W. C. (1998). Long-term effects of the intrauterine environment, birth weight, and breast-feeding in Pima Indians Diabetes Care, 21 Suppl 2(#issue#), B138-41 | Study design, Intervention/exposure
2020 | Peyre, H.,Bernard, J. Y.,Forhan, A.,Charles, M. A.,De Agostini, M.,Heude, B.,Ramus, F.,Charles, M. A.,De Agostini, M.,Forhan, A.,Heude, B.,Ducimetière, P.,Kaminski, M.,Saurel-Cubizolles, M. J.,Dargent, P.,Fritel, X.,Larroque, B.,Lelong, N.,Marchand, L.,Nabet, C.,Annesi-Maesano, I.,Slama, R.,Goua, V.,Magnin, G.,Hankard, R.,Thiebaugeorges, O.,Schweitzer, M.,Foliguet, B.,Job-Spira, N. (2014). Predicting changes in language skills between 2 and 3 years in the EDEN mother-child cohort PeerJ, 2014(1), #Pages# | Outcome
2021 | Pfluger, M.,Winkler, C.,Hummel, S.,Ziegler, A. G. (2010). Early infant diet in children at high risk for type 1 diabetes Horm Metab Res, 42(2), 143-8 | Intervention/exposure
2022 | Picciano, M. F.,Deering, R. H. (1980). The influence of feeding regimens on iron status during infancy Am J Clin Nutr, 33(4), 746-53 | Size of study groups, Intervention/exposure
2023 | Picone, T. A.,Benson, J. D.,Moro, G.,Minoli, I.,Fulconis, F.,Rassin, D. K.,Raiha, N. C. (1989). Growth, serum biochemistries, and amino acids of term infants fed formulas with amino acid and protein concentrations similar to human milk J Pediatr Gastroenterol Nutr, 9(3), 351-60 | Intervention/exposure, Outcome
2024 | Piemontese, P.,Gianni, M. L.,Braegger, C. P.,Chirico, G.,Gruber, C.,Riedler, J.,Arslanoglu, S.,van Stuijvenberg, M.,Boehm, G.,Jelinek, J.,Roggero, P. (2011). Tolerance and safety evaluation in a large cohort of healthy infants fed an innovative prebiotic formula: a randomized controlled trial PLoS One, 6(11), e28010 | Intervention/exposure
2025 | Pinho, A. P.,Aerts, D.,Nunes, M. L. (2008). Risk factors for sudden infant death syndrome in a developing country Rev Saude Publica, 42(3), 396-401 | Size of study groups, Intervention/exposure
2026 | Pinzon-Rondon, A. M.,Aguilera-Otalvaro, P.,Zarate-Ardila, C.,Hoyos-Martinez, A. (2015). Acute respiratory infection in children from developing nations: a multi-level study Paediatr Int Child Health, #volume#(#issue#), 2046905515y0000000021 | Study design
2027 | Pires, S. C.,Giugliani, E. R.,Caramez da Silva, F. (2012). Influence of the duration of breastfeeding on quality of muscle function during mastication in preschoolers: a cohort study BMC Public Health, 12(1), 934 | Outcome
2028 | Pirila, S.,Saarinen-Pihkala, U. M.,Viljakainen, H.,Turanlahti, M.,Kajosaari, M.,Makitie, O.,Taskinen, M. (2012). Breastfeeding and determinants of adult body composition: a prospective study from birth to young adulthood Horm Res Paediatr, 77(5), 281-90 | Outcome
2029 | Pirila, S.,Taskinen, M.,Viljakainen, H.,Kajosaari, M.,Turanlahti, M.,Saarinen-Pihkala, U. M.,Makitie, O. (2011). Infant milk feeding influences adult bone health: a prospective study from birth to 32 years PLoS One, 6(4), e19068 | Outcome
2030 | Pirila, S.,Taskinen, M.,Viljakainen, H.,Makitie, O.,Kajosaari, M.,Saarinen-Pihkala, U. M.,Turanlahti, M. (2014). Breast-fed infants and their later cardiovascular health: a prospective study from birth to age 32 years Br J Nutr, 111(6), 1069-76 | Outcome
2031 | Pisacane, A.,De Vizia, B.,Valiante, A.,Vaccaro, F.,Russo, M.,Grillo, G.,Giustardi, A. (1995). Iron status in breast-fed infants J Pediatr, 127(3), 429-31 | Size of study groups
2032 | Pisacane, A.,Graziano, L.,Zona, G.,Granata, G.,Dolezalova, H.,Cafiero, M.,Coppola, A.,Scarpellino, B.,Ummarino, M.,Mazzarella, G. (1994). Breast feeding and acute lower respiratory infection Acta Paediatr, 83(7), 714-8 | Study design, Participant health
2033 | Pivik, R. T.,Andres, A.,Badger, T. M. (2011). Diet and gender influences on processing and discrimination of speech sounds in 3- and 6-month-old infants: a developmental ERP study Dev Sci, 14(4), 700-12 | Outcome
2034 | Pivik, R. T.,Andres, A.,Badger, T. M. (2012). Effects of diet on early stage cortical perception and discrimination of syllables differing in voice-onset time: a longitudinal ERP study in 3 and 6 month old infants Brain Lang, 120(1), 27-41 | Outcome
2035 | Pivik, R. T.,Andres, A.,Tennal, K. B.,Gu, Y.,Armbya, N.,Cleves, M. A.,Badger, T. M. (2013). Infant diet, gender and the normative development of vagal tone and heart period during the first two years of life Int J Psychophysiol, 90(3), 311-20 | Outcome
2036 | Pivik, R. T.,Andres, A.,Tennal, K. B.,Gu, Y.,Cleves, M. A.,Badger, T. M. (2015). Infant diet, gender and the development of vagal tone stability during the first two years of life Int J Psychophysiol, 96(2), 104-14 | Outcome
2037 | Pivik, R. T.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M. (2007). The influence of infant diet on early developmental changes in processing human voice speech stimuli: ERP variations in breast and milk formula-fed infants at 3 and 6 months after birth Dev Neuropsychol, 31(3), 279-335 | Size of study groups
2038 | Pivik, R. T.,Dykman, R. A.,Jing, H.,Gilchrist, J. M.,Badger, T. M. (2009). Early infant diet and the omega 3 fatty acid DHA: effects on resting cardiovascular activity and behavioral development during the first half-year of life Dev Neuropsychol, 34(2), 139-58 | Size of study groups
2039 | Piwoz, E. G.,Creed de Kanashiro, H.,Lopez de Romana, G. L.,Black, R. E.,Brown, K. H. (1996). Feeding practices and growth among low-income Peruvian infants: a comparison of internationally-recommended definitions Int J Epidemiol, 25(1), 103-14 | Size of study groups, Intervention/exposure
2040 | Pizarro, F.,Yip, R.,Dallman, P. R.,Olivares, M.,Hertrampf, E.,Walter, T. (1991). Iron status with different infant feeding regimens: relevance to screening and prevention of iron deficiency J Pediatr, 118(5), 687-92 | Study design, Intervention/exposure
2041 | Plachta-Danielzik, S.,Kehden, B.,Landsberg, B.,Schaffrath Rosario, A.,Kurth, B. M.,Arnold, C.,Graf, C.,Hense, S.,Ahrens, W.,Muller, M. J. (2012). Attributable risks for childhood overweight: evidence for limited effectiveness of prevention Pediatrics, 130(4), e865-71 | Study design
2042 | Plagemann, A.,Harder, T.,Franke, K.,Kohlhoff, R. (2002). Long-term impact of neonatal breast-feeding on body weight and glucose tolerance in children of diabetic mothers Diabetes Care, 25(1), 16-22 | Intervention/exposure
2043 | Plagemann, A.,Harder, T.,Kohlhoff, R.,Fahrenkrog, S.,Rodekamp, E.,Franke, K.,Dudenhausen, J. W. (2005). Impact of early neonatal breast-feeding on psychomotor and neuropsychological development in children of diabetic mothers Diabetes Care, 28(3), 573-8 | Intervention/exposure
2044 | Plagemann, A.,Harder, T.,Rodekamp, E.,Kohlhoff, R. (2012). Rapid neonatal weight gain increases risk of childhood overweight in offspring of diabetic mothers J Perinat Med, 40(5), 557-63 | Intervention/exposure
2045 | Plancoulaine, S.,Charles, M. A.,Lafay, L.,Tauber, M.,Thibult, N.,Borys, J. M.,Eschwege, E. (2000). Infant-feeding patterns are related to blood cholesterol concentration in prepubertal children aged 5-11 y: the Fleurbaix-Laventie Ville Sante study Eur J Clin Nutr, 54(2), 114-9 | Outcome
2046 | Plenge-Bonig, A.,Soto-Ramirez, N.,Karmaus, W.,Petersen, G.,Davis, S.,Forster, J. (2010). Breastfeeding protects against acute gastroenteritis due to rotavirus in infants Eur J Pediatr, 169(12), 1471-6 | Study design, Intervention/exposure
2047 | Plonka, K. A.,Pukallus, M. L.,Barnett, A. G.,Walsh, L. J.,Holcombe, T. F.,Seow, W. K. (2012). A longitudinal study comparing mutans streptococci and lactobacilli colonisation in dentate children aged 6 to 24 months Caries Res, 46(4), 385-93 | Outcome
2048 | Plonka, K. A.,Pukallus, M. L.,Barnett, A. G.,Walsh, L. J.,Holcombe, T. H.,Seow, W. K. (2012). Mutans streptococci and lactobacilli colonization in predentate children from the neonatal period to seven months of age Caries Res, 46(3), 213-20 | Outcome
2049 | Podratz, R. O.,Broughton, D. D.,Gustafson, D. H.,Bergstralh, E. J.,Melton, L. J., 3rd (1986). Weight loss and body temperature changes in breast-fed and bottle-fed neonates Clin Pediatr (Phila), 25(2), 73-7 | Outcome
2050 | Pohlabeln, H.,Muhlenbruch, K.,Jacobs, S.,Bohmann, H. (2010). Frequency of allergic diseases in 2-year-old children in relationship to parental history of allergy and breastfeeding J Investig Allergol Clin Immunol, 20(3), 195-200 | Intervention/exposure
2051 | Poikonen, S.,Puumalainen, T. J.,Kautiainen, H.,Palosuo, T.,Reunala, T.,Turjanmaa, K. (2008). Sensitization to turnip rape and oilseed rape in children with atopic dermatitis: a case-control study Pediatr Allergy Immunol, 19(5), 408-11 | Intervention/exposure
2052 | Pollock, J. I. (1994). Long-term associations with infant feeding in a clinically advantaged population of babies Dev Med Child Neurol, 36(5), 429-40 | Intervention/exposure
2053 | Pomerance, H. H. (1987). Growth in breast-fed children Hum Biol, 59(4), 687-93 | Intervention/exposure
2054 | Ponder, D. L.,Innis, S. M.,Benson, J. D.,Siegman, J. S. (1992). Docosahexaenoic acid status of term infants fed breast milk or infant formula containing soy oil or corn oil Pediatr Res, 32(6), 683-8 | Size of study groups
2055 | Ponnapakkam, T.,Ravichandran, A.,Bradford, E.,Tobin, G.,Gensure, R. (2008). Breast-feeding and vitamin D supplementation rates in the Ochsner health system Ochsner Journal, 8(3), 146-150 | Intervention/exposure, Outcome
2056 | Porro, E.,Indinnimeo, L.,Antognoni, G.,Midulla, F.,Criscione, S. (1993). Early wheezing and breast feeding J Asthma, 30(1), 23-8 | Outcome
2057 | Portela, D. S.,Vieira, T. O.,Matos, S. M.,de Oliveira, N. F.,Vieira, G. O. (2015). Maternal obesity, environmental factors, cesarean delivery and breastfeeding as determinants of overweight and obesity in children: results from a cohort BMC Pregnancy Childbirth, 15(#issue#), 94 | Outcome
2058 | Portoian-Shuhaiber, S.,Al-Rashied, A. A. (1986). Feeding practices and electrolyte disturbances among infants admitted with acute diarrhoea--a survey in Kuwait J Trop Pediatr, 32(4), 168-73 | Study design, Participant health
2059 | Potera, Carol (2011). Prolonged Bottle Feeding Raises Childhood Obesity Risk: Weaning around one year is recommended American Journal of Nursing, 111(8), 17-17 1p | Study design
2060 | Potter, A.,Lumley, J.,Watson, L. (1996). The ‘new’ risk factors for SIDS: is there an association with the ethnic and place of birth differences in incidence in Victoria, Australia? Early Hum Dev, 45(1-2), 119-31 | Intervention/exposure, Outcome
2061 | Potter, C. M.,Ulijaszek, S. J. (2013). Predicting adult obesity from measures in earlier life J Epidemiol Community Health, 67(12), 1032-7 | Study design, Intervention/exposure
2062 | Potur, A. H.,Kalmaz, N. (1995). An investigation into feeding errors of 0-4-month-old infants J Trop Pediatr, 41(2), 120-2 | Study design
2063 | Poysa, L. (1989). Atopy in children with and without a family history of atopy. II. Skin reactivity Acta Paediatr Scand, 78(6), 902-6 | Intervention/exposure
2064 | Poysa, L.,Korppi, M.,Remes, K.,Juntunen-Backman, K. (1990). Predictive value of IgE levels in infancy Acta Paediatr Scand, 79(10), 970-2 | Study design, Outcome
2065 | Poysa, L.,Korppi, M.,Remes, K.,Juntunen-Backman, K. (1991). Atopy in childhood and diet in infancy. A nine-year follow-up study. I. Clinical manifestations Allergy Proc, 12(2), 107-11 | Size of study groups
2066 | Poysa, L.,Remes, K.,Korppi, M.,Juntunen-Backman, K. (1989). Atopy in children with and without a family history of atopy. I. Clinical manifestations, with special reference to diet in infancy Acta Paediatr Scand, 78(6), 896-901 | Size of study groups
2067 | Prado-Montes de Oca, E.,Garcia-Vargas, A.,Lozano-Inocencio, R.,Gallegos-Arreola, M. P.,Sandoval-Ramirez, L.,Davalos-Rodriguez, N. O.,Figuera, L. E. (2007). Association of beta-defensin 1 single nucleotide polymorphisms with atopic dermatitis Int Arch Allergy Immunol, 142(3), 211-8 | Study design
2068 | Prado-Montes De Oca, E.,García-Vargas, A.,Lozano-Inocencio, R.,Gallegos-Arreola, M. P.,Sandoval-Ramírez, L.,Dávalos-Rodríguez, N. O.,Figuera, L. E. (2007). Association of β-defensin 1 single nucleotide polymorphisms with atopic dermatitis International Archives of Allergy and Immunology, 142(3), 211-218 | Study design
2069 | Prathanee, B.,Purdy, S. C.,Thinkhamrop, B.,Chaimay, B.,Ruangdaraganon, N.,Mo-suwan, L.,Phuphaibul, R. (2009). Early language delay and predictive factors in children aged 2 years J Med Assoc Thai, 92(7), 930-8 | Outcome
2070 | Pratt, H. F. (1984). Breastfeeding and eczema Early Hum Dev, 9(3), 283-90 | Intervention/exposure
2071 | Prentice, P.,Koulman, A.,Matthews, L.,Acerini, C. L.,Ong, K. K.,Dunger, D. B. (2015). Lipidomic analyses, breast- and formula-feeding, and growth in infants J Pediatr, 166(2), 276-81 e6 | Intervention/exposure
2072 | Price, Gareth (2011). A test of temperament Midwives, 14(4), 13-13 1p | Study design
2073 | Priego, T.,Sanchez, J.,Pico, C.,Ahrens, W.,Bammann, K.,De Henauw, S.,Fraterman, A.,Iacoviello, L.,Lissner, L.,Molnar, D.,Moreno, L. A.,Siani, A.,Tornaritis, M.,Veidebaum, T.,Palou, A. (2014). Influence of breastfeeding on blood-cell transcript-based biomarkers of health in children Pediatr Obes, 9(6), 463-70 | Study design, Outcome
2074 | Priya, N. Gayathri,Victoria, L. Eilean,Porkodi, A.,Eaton, Linda,Doorenbos, Ardith (2013). Effectiveness of Breastfeeding Empowerment Programme among Primigravidae Communicating Nursing Research, 46(#issue#), 579-579 1p | Country
2075 | Procter, S. B.,Holcomb, C. A. (2008). Breastfeeding duration and childhood overweight among low-income children in Kansas, 1998-2002 Am J Public Health, 98(1), 106-10 | Outcome
2076 | Prodam, F.,Roccio, M.,Trovato, L.,Ricotti, R.,Moia, S.,Giglione, E.,Petri, A.,Walker, G. E.,Bellone, S.,Bona, G. (2015). Adiponectin oligomers are similarly distributed in adequate-for-gestational-age obese children irrespective of feeding in their first year Pediatr Res, 77(6), 808-13 | Study design
2077 | Puccio, G.,Cajozzo, C.,Meli, F.,Rochat, F.,Grathwohl, D.,Steenhout, P. (2007). Clinical evaluation of a new starter formula for infants containing live Bifidobacterium longum BL999 and prebiotics Nutrition, 23(1), 1-8 | Intervention/exposure
2078 | Pugh, L. C.,Milligan, R. A. (1998). Nursing intervention to increase the duration of breastfeeding Appl Nurs Res, 11(4), 190-4 | Study design, Outcome
2079 | Pugh, L. C.,Milligan, R. A.,Frick, K. D.,Spatz, D.,Bronner, Y. (2002). Breastfeeding duration, costs, and benefits of a support program for low-income breastfeeding women Birth, 29(2), 95-100 | Size of study groups
2080 | Pugo-Gunsam, P.,Guesnet, P.,Subratty, A. H.,Rajcoomar, D. A.,Maurage, C.,Couet, C. (1999). Fatty acid composition of white adipose tissue and breast milk of Mauritian and French mothers and erythrocyte phospholipids of their full-term breast-fed infants Br J Nutr, 82(4), 263-71 | Size of study groups, Intervention/exposure
2081 | Puig, C.,Sunyer, J.,Garcia-Algar, O.,Munoz, L.,Pacifici, R.,Pichini, S.,Vall, O. (2008). Incidence and risk factors of lower respiratory tract illnesses during infancy in a Mediterranean birth cohort Acta Paediatr, 97(10), 1406-11 | Outcome
2082 | Pukander J,Luotonen J,Timonen M,Karma P (1985). Risk factors affecting the occurrence of acute otitis media among 2-3-year-old urban children Acta Otolaryngol, 100(#issue#), 260-5 | Outcome
2083 | Pukander, J. (1982). Acute otitis media among rural children in Finland Int J Pediatr Otorhinolaryngol, 4(4), 325-32 | Outcome
2084 | Pullan, C. R.,Toms, G. L.,Martin, A. J.,Gardner, P. S.,Webb, J. K.,Appleton, D. R. (1980). Breast-feeding and respiratory syncytial virus infection Br Med J, 281(6247), 1034-6 | Outcome
2085 | Purssell, E. (2012). A topic in 10 questions: Gastrointestinal infections from a nutritional perspective J Fam Health Care, 22(1), 28-9 | Study design
2086 | Purvis, D. J.,Thompson, J. M.,Clark, P. M.,Robinson, E.,Black, P. N.,Wild, C. J.,Mitchell, E. A. (2005). Risk factors for atopic dermatitis in New Zealand children at 3.5 years of age Br J Dermatol, 152(4), 742-9 | Outcome
2087 | Putet, G.,Labaune, J. M.,Mace, K.,Steenhout, P.,Grathwohl, D.,Raverot, V.,Morel, Y.,Picaud, J. C. (2015). Effect of dietary protein on plasma insulin-like growth factor-1, growth, and body composition in healthy term infants: a randomised, double-blind, controlled trial (Early Protein and Obesity in Childhood (EPOCH) study) Br J Nutr, #volume#(#issue#), 1-14 | Intervention/exposure
2088 | Putnam, J. C.,Carlson, S. E.,DeVoe, P. W.,Barness, L. A. (1982). The effect of variations in dietary fatty acids on the fatty acid composition of erythrocyte phosphatidylcholine and phosphatidylethanolamine in human infants Am J Clin Nutr, 36(1), 106-14 | Size of study groups
2089 | Putra, S. T.,Mansyur, M.,Sastroasmoro, S. (2015). Effects of duration of breastfeeding during infancy on vascular dysfunction in adolescents Acta Med Indones, 47(1), 24-30 | Country, Study design
2090 | Qudsia, F.,Saboor, M.,Khosa, S. M.,Ayub, Q.,Moinuddin, (2015). Comparative analysis of serum iron, serum ferritin and red cell folate levels among breast fed, fortified milk and cow’s milk fed infants Pakistan Journal of Medical Sciences, 31(3), 706-709 | Country
2091 | Queiroz, V. A.,Assis, A. M.,Pinheiro, S. M.,Ribeiro, H. C., Jr. (2012). Predictors of linear growth in the first year of life of a prospective cohort of full term children with normal birth weight J Pediatr (Rio J), 88(1), 79-86 | Intervention/exposure
2092 | Quialey, M. A.,Cumberland, P.,Cowden, J. M.,Rodrigues, L. C. (2006). How protective is breast feeding against diarrhoeal disease in infants in 1990s England? A case-control study Archives of Disease in Childhood, 91(3), 245-250 | Outcome
2093 | Quigley, M. A.,Hockley, C.,Carson, C.,Kelly, Y.,Renfrew, M. J.,Sacker, A. (2012). Breastfeeding is associated with improved child cognitive development: a population-based cohort study J Pediatr, 160(1), 25-32 | Outcome
2094 | Quigley, M. A.,Kelly, Y. J.,Sacker, A. (2007). Breastfeeding and hospitalization for diarrheal and respiratory infection in the United Kingdom Millennium Cohort Study Pediatrics, 119(4), e837-42 | Study design
2095 | Quigley, M. A.,Kelly, Y. J.,Sacker, A. (2009). Infant feeding, solid foods and hospitalisation in the first 8 months after birth Arch Dis Child, 94(2), 148-50 | Intervention/exposure
2096 | Quinn, P. J.,O’Callaghan, M.,Williams, G. M.,Najman, J. M.,Andersen, M. J.,Bor, W. (2001). The effect of breastfeeding on child development at 5 years: a cohort study J Paediatr Child Health, 37(5), 465-9 | Outcome
2097 | Quinonez, R.,Santos, R. G.,Wilson, S.,Cross, H. (2001). The relationship between child temperament and early childhood caries Pediatr Dent, 23(1), 5-10 | Study design
2098 | Quiroga, M.,Oviedo, P.,Chinen, I.,Pegels, E.,Husulak, E.,Binztein, N.,Rivas, M.,Schiavoni, L.,Vergara, M. (2000). Asymptomatic infections by diarrheagenic Escherichia coli in children from Misiones, Argentina, during the first twenty months of their lives Rev Inst Med Trop Sao Paulo, 42(1), 9-15 | Outcome
2099 | Qureshi, B.,Morgan, J. B.,Kimer, A. C.,Donaldson, D.,Dickerson, J. W. (1988). Feeding practices and birth weights of infants in Southall, Middlesex J R Soc Health, 108(3), 77-80 | Outcome
2100 | Rabiei, S. (2011). The Association of Nutrition Style through the First 2 Years of Life with Type 1 Diabetes Mellitus and Some of the Other Effective Factors in 2-15 Years Old Children Iranian Journal of Endocrinology & Metabolism, 13(1), 9-113 105p | Language
2101 | Radlovic, N. P.,Mladenovic, M. M.,Lekovic, Z. M.,Stojsic, Z. M.,Radlovic, V. N. (2010). Influence of early feeding practices on celiac disease in infants Croat Med J, 51(5), 417-22 | Participant health, Intervention/exposure
2102 | Rady, H. I.,Samir, H.,Tomerak, R.,Gaafar, M. (2014). Occult blood in stool in exclusively formula fed infants versus exclusively breast fed infants in the first six months of life Egyptian Pediatric Association Gazette, 62(1), 8-13 | Country, Study design
2103 | Raftowicz-Wójcik, K.,Matthews-Brzozowska, T.,Kawala, B.,Antoszewska, J. (2011). The effects of breast feeding on occlusion in primary dentition Advances in Clinical and Experimental Medicine, 20(3), 371-375 | Study design
2104 | Rahman, M.,Roy, S. K.,Ali, M.,Mitra, A. K.,Alam, A. N.,Akbar, M. S. (1993). Maternal nutritional status as a determinant of child health J Trop Pediatr, 39(2), 86-8 | Country
2105 | Raiha, N. C.,Fazzolari-Nesci, A.,Boehm, G. (1996). Taurine supplementation prevents hyperaminoacidemia in growing term infants fed high-protein cow’s milk formula Acta Paediatr, 85(12), 1403-7 | Size of study groups
2106 | Raiha, N. C.,Fazzolari-Nesci, A.,Cajozzo, C.,Puccio, G.,Monestier, A.,Moro, G.,Minoli, I.,Haschke-Becher, E.,Bachmann, C.,Van’t Hof, M.,Carrie Fassler, A. L.,Haschke, F. (2002). Whey predominant, whey modified infant formula with protein/energy ratio of 1.8 g/100 kcal: adequate and safe for term infants from birth to four months J Pediatr Gastroenterol Nutr, 35(3), 275-81 | Intervention/exposure
2107 | Räihä, N.,Fazzolari, A.,Cayozzo, C.,Puccio, G.,Minoli, I.,Moro, G.,Monestier, A.,Haschke-Becher, E.,Carrié, A. L.,Haschke, F. (2002). Infant formula with 1.8g Protein/100 Kcal is adequate and safe from birth to 4 months Revue Medicale Libanaise, 14(1), 29-31 | Size of study groups
2108 | Raiha, N.,Minoli, I.,Moro, G. (1986). Milk protein intake in the term infant. I. Metabolic responses and effects on growth Acta Paediatr Scand, 75(6), 881-6 | Size of study groups
2109 | Raisler, J.,Alexander, C.,O’Campo, P. (1999). Breast-feeding and infant illness: a dose-response relationship? Am J Public Health, 89(1), 25-30 | Study design, Participant health
2110 | Ramezani, G. H.,Norozi, A.,Valael, N. (2003). The prevalence of nursing caries in 18 to 60 months old children in Qazvin J Indian Soc Pedod Prev Dent, 21(1), 19-26 | Study design
2111 | Rami, B.,Schneider, U.,Imhof, A.,Waldhor, T.,Schober, E. (1999). Risk factors for type I diabetes mellitus in children in Austria Eur J Pediatr, 158(5), 362-6 | Outcome
2112 | Ramirez, G. B.,Pagulayan, O.,Akagi, H.,Francisco Rivera, A.,Lee, L. V.,Berroya, A.,Vince Cruz, M. C.,Casintahan, D. (2003). Tagum study II: follow-up study at two years of age after prenatal exposure to mercury Pediatrics, 111(3), e289-95 | Country
2113 | Ramirez-Silva, I.,Rivera, J. A.,Trejo-Valdivia, B.,Martorell, R.,Stein, A. D.,Romieu, I.,Barraza-Villarreal, A.,Ramakrishnan, U. (2015). Breastfeeding status at age 3 months is associated with adiposity and cardiometabolic markers at age 4 years in Mexican children J Nutr, 145(6), 1295-302 | Outcome
2114 | Ramirez-Silva, I.,Rivera, J.,Martorell, R.,Stein, A.,Ramakrishnan, U. (2013). Breastfeeding at 3 months is associated with lower risk of adiposity and lipid metabolism alterations at 4 y of age Annals of nutrition & metabolism, 63(#issue#), 774-5 | Publication status
2115 | Ramos, D. E. (2012). Breastfeeding: a bridge to addressing disparities in obesity and health Breastfeed Med, 7(5), 354-7 | Study design
2116 | Ramos-Gomez, F. J.,Tomar, S. L.,Ellison, J.,Artiga, N.,Sintes, J.,Vicuna, G. (1999). Assessment of early childhood caries and dietary habits in a population of migrant Hispanic children in Stockton, California ASDC J Dent Child, 66(6), 395-403, 366 | Study design
2117 | Rannan-Eliya, R. P.,Hossain, S. M.,Anuranga, C.,Wickramasinghe, R.,Jayatissa, R.,Abeykoon, A. T. (2013). Trends and determinants of childhood stunting and underweight in Sri Lanka Ceylon Med J, 58(1), 10-8 | Study design
2118 | Ransome, O. J.,Chalmers, B.,Herman, A. A.,Reinach, S. G. (1988). Infant feeding in an urban community S Afr Med J, 74(8), 393-5 | Country, Study design
2119 | Rao, M. R.,Hediger, M. L.,Levine, R. J.,Naficy, A. B.,Vik, T. (2002). Effect of breastfeeding on cognitive development of infants born small for gestational age Acta Paediatr, 91(3), 267-74 | Participant health, Intervention/exposure
2120 | Rao, S.,Kanade, A. N. (1992). Prolonged breast-feeding and malnutrition among rural Indian children below 3 years of age Eur J Clin Nutr, 46(3), 187-95 | Country
2121 | Rao, S.,Rajpathak, V. (1992). Breastfeeding and weaning practices in relation to nutritional status of infants Indian pediatrics, 29(12), 1533-1539 | Country
2122 | Rasmussen, K. M.,Kjolhede, C. L. (2008). Maternal obesity: a problem for both mother and child Obesity (Silver Spring), 16(5), 929-31 | Study design
2123 | Rassin, D. K.,Raiha, N. C.,Minoli, I.,Moro, G. (1990). Taurine and cholesterol supplementation in the term infant: responses of growth and metabolism JPEN J Parenter Enteral Nutr, 14(4), 392-7 | Size of study groups
2124 | Ratageri, V. H.,Kabra, S. K.,Dwivedi, S. N.,Seth, V. (2000). Factors associated with severe asthma Indian Pediatr, 37(10), 1072-82 | Country
2125 | Rathnayake, K. M.,Satchithananthan, A.,Mahamithawa, S.,Jayawardena, R. (2013). Early life predictors of preschool overweight and obesity: a case-control study in Sri Lanka BMC Public Health, 13(#issue#), 994 | Study design, Intervention/exposure
2126 | Ravelli, A. C.,van der Meulen, J. H.,Osmond, C.,Barker, D. J.,Bleker, O. P. (2000). Infant feeding and adult glucose tolerance, lipid profile, blood pressure, and obesity Arch Dis Child, 82(3), 248-52 | Intervention/exposure
2127 | Rawashdeh, M. O.,Khalil, B.,Raweily, E. (1996). Celiac disease in Arabs J Pediatr Gastroenterol Nutr, 23(4), 415-8 | Study design, Intervention/exposure, Participant health
2128 | Ray G (1985). Infant feeding. Psychology of choice Nurs Mirror, 160(#issue#), 25-8 | Study design
2129 | Reading, R. (2008). Effects of prolonged and exclusive breastfeeding on child behavior and maternal adjustment: evidence from a large, randomized trial…Kramer MS, Fombonne E, Igumnov S, Vanilovich L, Matush L, Mironova E, Bogdanovich N, Tremblay RE, Chalmers B, Zhang X & Platt RW for the PROBIT study group (2008) Pediatrics, 121, E435-40 Child: Care, Health & Development, 34(4), 547-547 1p | Publication status
2130 | Rebhan, B.,Kohlhuber, M.,Schwegler, U.,Fromme, H.,Abou-Dakn, M.,Koletzko, B. V. (2009). Breastfeeding duration and exclusivity associated with infants’ health and growth: data from a prospective cohort study in Bavaria, Germany Acta Paediatr, 98(6), 974-80 | Intervention/exposure
2131 | Regnault, N.,Botton, J.,Blanc, L.,Hankard, R.,Forhan, A.,Goua, V.,Thiebaugeorges, O.,Kaminski, M.,Heude, B.,Charles, M. A. (2011). Determinants of neonatal weight loss in term-infants: specific association with pre-pregnancy maternal body mass index and infant feeding mode Arch Dis Child Fetal Neonatal Ed, 96(3), F217-22 | Outcome
2132 | Regnault, N.,Botton, J.,Forhan, A.,Hankard, R.,Thiebaugeorges, O.,Hillier, T. A.,Kaminski, M.,Heude, B.,Charles, M. A. (2010). Determinants of early ponderal and statural growth in full-term infants in the EDEN mother-child cohort study Am J Clin Nutr, 92(3), 594-602 | Outcome
2133 | Reid, A. (2002). Infant feeding and post-neonatal mortality in Derbyshire, England, in the early twentieth century Popul Stud (Camb), 56(2), 151-66 | Intervention/exposure, Outcome
2134 | Renn, M. (1987). Baby milk: is breast second best? Nurs Times, 83(6), 19-20 | Study design
2135 | Rennie, A. M.,Rowand, J. (2012). The beautiful game and breastfeeding Pract Midwife, 15(9), 46 | Study design
2136 | Renz, H.,Brehler, C.,Petzoldt, S.,Prinz, H.,Rieger, C. H. (1991). Breast feeding modifies production of SIgA cow’s milk-antibodies in infants Acta Paediatr Scand, 80(2), 149-54 | Outcome
2137 | Reyes Romagosa, D. E.,Paneque Gamboa, M. R.,Almeida Muniz, Y.,Quesada Oliva, L. M.,Escalona Oliva, D.,Torres Naranjo, S. (2014). Risk factors associated with deforming oral habits in children aged 5 to 11: a case-control study Medwave, 14(2), e5927 | Language
2138 | Reyes, H.,Perez-Cuevas, R.,Salmeron, J.,Tome, P.,Guiscafre, H.,Gutierrez, G. (1997). Infant mortality due to acute respiratory infections: the influence of primary care processes Health Policy Plan, 12(3), 214-23 | Participant health, Intervention/exposure
2139 | Reyes, H.,Perez-Cuevas, R.,Sandoval, A.,Castillo, R.,Santos, J. I.,Doubova, S. V.,Gutierrez, G. (2004). The family as a determinant of stunting in children living in conditions of extreme poverty: a case-control study BMC Public Health, 4(#issue#), 57 | Study design
2140 | Reyes, M.,Hoyos, V.,Martinez, S. M.,Lozoff, B.,Castillo, M.,Burrows, R.,Blanco, E.,Gahagan, S. (2014). Satiety responsiveness and eating behavior among Chilean adolescents and the role of breastfeeding Int J Obes (Lond), 38(4), 552-7 | Intervention/exposure
2141 | Reynolds, D.,Hennessy, E.,Polek, E. (2014). Is breastfeeding in infancy predictive of child mental well-being and protective against obesity at 9 years of age? Child Care Health Dev, 40(6), 882-90 | Study design
2142 | Rhodes C (1982). The benefits of breast-feeding J Pract Nurs, 32(#issue#), 19-21, 54-5 | Study design
2143 | Ribadeau-Dumas, B. (1983). Human milk Endeavour, 7(2), 80-7 | Study design
2144 | Ribas-Fito, N.,Cardo, E.,Sala, M.,Eulalia de Muga, M.,Mazon, C.,Verdu, A.,Kogevinas, M.,Grimalt, J. O.,Sunyer, J. (2003). Breastfeeding, exposure to organochlorine compounds, and neurodevelopment in infants Pediatrics, 111(5 Pt 1), e580-5 | Size of study groups
2145 | Ribas-Fito, N.,Julvez, J.,Torrent, M.,Grimalt, J. O.,Sunyer, J. (2007). Beneficial effects of breastfeeding on cognition regardless of DDT concentrations at birth Am J Epidemiol, 166(10), 1198-202 | Intervention/exposure
2146 | Ricco, R. G.,Nogueira-de-Almeida, C. A.,Del Ciampo, L. A.,Daneluzzi, J. C.,Ferlin, M. L.,Muccillo, G. (2001). Growth of exclusively breast-fed infants from a poor urban population Arch Latinoam Nutr, 51(2), 122-6 | Intervention/exposure
2147 | Richards, M.,Hardy, R.,Wadsworth, M. E. (2002). Long-term effects of breast-feeding in a national birth cohort: educational attainment and midlife cognitive function Public Health Nutr, 5(5), 631-5 | Outcome
2148 | Richards, M.,Wadsworth, M.,Rahimi-Foroushani, A.,Hardy, R.,Kuh, D.,Paul, A. (1998). Infant nutrition and cognitive development in the first offspring of a national UK birth cohort Dev Med Child Neurol, 40(3), 163-7 | Intervention/exposure
2149 | Richardson, B. D.,Cleaton-Jones, P. E.,McInnes, P. M.,Rantsho, J. M. (1981). Infant feeding practices and nursing bottle caries ASDC J Dent Child, 48(6), 423-9 | Study design, Outcome
2150 | Rich-Edwards, J. W.,Stampfer, M. J.,Manson, J. E.,Rosner, B.,Hu, F. B.,Michels, K. B.,Willett, W. C. (2004). Breastfeeding during infancy and the risk of cardiovascular disease in adulthood Epidemiology, 15(5), 550-6 | Intervention/exposure
2151 | Richman, D.,Dixon, S. (1985). Comparative study of Cambodian, Hmong, and Caucasian infant and maternal perinatal profiles J Nurse Midwifery, 30(6), 313-9 | Intervention/exposure
2152 | Rigas, A.,Rigas, B.,Glassman, M.,Yen, Y. Y.,Shou Jen, Lan,Petridou, E.,Hsieh, C. C.,Trichopoulos, D. (1993). Breast-feeding and maternal smoking in the etiology of Crohn’s disease and ulcerative colitis in childhood Annals of Epidemiology, 3(4), 387-392 | Outcome
2153 | Rigby, A. S.,Sanderson, C.,Desforges, M. F.,Lindsay, G.,Hall, D. M. (1999). The infant index: a new outcome measure for pre-school children’s services J Public Health Med, 21(2), 172-8 | Outcome
2154 | Rigo, J.,Salle, B. L.,Cavero, E.,Richard, P.,Putet, G.,Senterre, J. (1994). Plasma amino acid and protein concentrations in infants fed human milk or a whey protein hydrolysate formula during the first month of life Acta Paediatr, 83(2), 127-31 | Size of study groups
2155 | Rigo, J.,Salle, B. L.,Picaud, J. C.,Putet, G.,Senterre, J. (1995). Nutritional evaluation of protein hydrolysate formulas Eur J Clin Nutr, 49 Suppl 1(#issue#), S26-38 | Size of study groups
2156 | Riordan, J.,Countryman, B. A. (1980). Basics of breastfeeding. Part IV: Preparation for breastfeeding and early optimal functioning JOGN Nurs, 9(5), 277-83 | Study design, Outcome
2157 | Rios-Castillo, I.,Cerezo, S.,Corvalan, C.,Martinez, M.,Kain, J. (2015). Risk factors during the prenatal period and the first year of life associated with overweight in 7-year-old low-income Chilean children Matern Child Nutr, 11(4), 595-605 | Outcome
2158 | Riva, V.,Battaglia, M.,Nobile, M.,Cattaneo, F.,Lazazzera, C.,Mascheretti, S.,Giorda, R.,Merette, C.,Emond, C.,Maziade, M.,Marino, C. (2015). GRIN2B predicts attention problems among disadvantaged children Eur Child Adolesc Psychiatry, 24(7), 827-36 | Study design
2159 | Roberts AK (1987). Prospects for further approximation of infant formulae to human milk Midwife Health Visit Community Nurse, 23(#issue#), 140-6 | Study design, Outcome
2160 | Roberts, C. C.,Chan, G. M.,Folland, D.,Rayburn, C.,Jackson, R. (1981). Adequate bone mineralization in breast-fed infants J Pediatr, 99(2), 192-6 | Size of study groups
2161 | Roberts, D. W. (1980). Growth of breast fed and bottle fed infants N Z Med J, 92(664), 45-6 | Outcome
2162 | Roberts, G. J. (1982). Is breast feeding a possible cause of dental caries? J Dent, 10(4), 346-52 | Study design
2163 | Roberts, S. E.,Wotton, C. J.,Williams, J. G.,Griffith, M.,Goldacre, M. J. (2011). Perinatal and early life risk factors for inflammatory bowel disease World J Gastroenterol, 17(6), 743-9 | Outcome
2164 | Robertson, L.,Harrild, K. (2010). Maternal and neonatal risk factors for childhood type 1 diabetes: a matched case-control study BMC Public Health, 10(#issue#), 281 | Outcome
2165 | Robinson, M.,Oddy, W. H.,Li, J.,Kendall, G. E.,de Klerk, N. H.,Silburn, S. R.,Zubrick, S. R.,Newnham, J. P.,Stanley, F. J.,Mattes, E. (2008). Pre- and postnatal influences on preschool mental health: a large-scale cohort study J Child Psychol Psychiatry, 49(10), 1118-28 | Outcome
2166 | Robinson, S. M.,Crozier, S. R.,Harvey, N. C.,Barton, B. D.,Law, C. M.,Godfrey, K. M.,Cooper, C.,Inskip, H. M. (2015). Modifiable early-life risk factors for childhood adiposity and overweight: an analysis of their combined impact and potential for prevention Am J Clin Nutr, 101(2), 368-75 | Intervention/exposure
2167 | Robinson, S. M.,Marriott, L. D.,Crozier, S. R.,Harvey, N. C.,Gale, C. R.,Inskip, H. M.,Baird, J.,Law, C. M.,Godfrey, K. M.,Cooper, C. (2009). Variations in infant feeding practice are associated with body composition in childhood: a prospective cohort study J Clin Endocrinol Metab, 94(8), 2799-805 | Intervention/exposure
2168 | Rochat, F.,Cherbut, C.,Barclay, D.,Puccio, G.,Fazzolari-Nesci, A.,Grathwohl, D.,Haschke, F. (2007). A whey-predominant formula induces fecal microbiota similar to that found in breast-fed infants Nutrition Research, 27(12), 735-740 | Size of study groups, Outcome
2169 | Roche, A. F.,Guo, S.,Siervogel, R. M.,Khamis, H. J.,Chandra, R. K. (1993). Growth comparison of breast-fed and formula-fed infants Can J Public Health, 84(2), 132-5 | Outcome
2170 | Rodekamp, E.,Harder, T.,Kohlhoff, R.,Dudenhausen, J. W.,Plagemann, A. (2006). Impact of breast-feeding on psychomotor and neuropsychological development in children of diabetic mothers: role of the late neonatal period J Perinat Med, 34(6), 490-6 | Intervention/exposure
2171 | Rodekamp, E.,Harder, T.,Kohlhoff, R.,Franke, K.,Dudenhausen, J. W.,Plagemann, A. (2005). Long-term impact of breast-feeding on body weight and glucose tolerance in children of diabetic mothers: role of the late neonatal period and early infancy Diabetes Care, 28(6), 1457-62 | Outcome
2172 | Rodriguez Martinez, C.,Sossa, M.,Goss, C. H. (2008). Factors associated with severe disease in a population of asthmatic children of Bogota, Colombia J Asthma, 45(2), 141-7 | Study design
2173 | Rodriguez-Lopez, M.,Osorio, L.,Acosta-Rojas, R.,Figueras, J.,Cruz-Lemini, M.,Figueras, F.,Bijnens, B.,Gratacos, E.,Crispi, F. (2015). Influence of breastfeeding and postnatal nutrition on cardiovascular remodeling induced by fetal growth restriction Pediatr Res, #volume#(#issue#), #Pages# | Participant health, Intervention/exposure
2174 | Roelants, M.,Hauspie, R.,Hoppenbrouwers, K. (2010). Breastfeeding, growth and growth standards: Performance of the WHO growth standards for monitoring growth of Belgian children Ann Hum Biol, 37(1), 2-9 | Intervention/exposure
2175 | Rogan, W. J.,Gladen, B. C. (1993). Breast-feeding and cognitive development Early Hum Dev, 31(3), 181-93 | Outcome
2176 | Rolland-Cachera, M. F.,Peneau, S. (2011). Assessment of growth: variations according to references and growth parameters used Am J Clin Nutr, 94(6 Suppl), 1794S-1798S | Study design
2177 | Romano, A. M. (2006). Longer duration of breastfeeding is associated with lower risk of type-2 diabetes (abst; commentary) Journal of Perinatal Education, 15(2), 54-55 2p | Study design
2178 | Romero, C. C.,Scavone Jr, H.,Garib, D. G.,Cotrim-Ferreira, F. A.,Ferreira, I. R. (2011). Breastfeeding and non-nutritive sucking patterns related to the prevalence of anterior open bite in primary dentition Journal of Applied Oral Science, 19(2), 161-168 | Study design
2179 | Romieu, I.,Werneck, G.,Ruiz Velasco, S.,White, M.,Hernandez, M. (2000). Breastfeeding and asthma among Brazilian children J Asthma, 37(7), 575-83 | Study design
2180 | Rona, R. J.,Smeeton, N. C.,Bustos, P.,Amiga, H.,Diaz, P. V. (2005). The early origins hypothesis with an emphasis on growth rate in the first year of life and asthma: A prospective study in Chile Thorax, 60(7), 549-554 | Outcome
2181 | Rosas-Salazar, C.,Forno, E.,Brehm, J. M.,Han, Y. Y.,Acosta-Perez, E.,Cloutier, M. M.,Wakefield, D. B.,Alvarez, M.,Colon-Semidey, A.,Canino, G.,Celedon, J. C. (2015). Breastfeeding duration and asthma in Puerto Rican children Pediatr Pulmonol, 50(6), 527-34 | Outcome
2182 | Rose, C. M.,Savage, J. S.,Birch, L. L. (2016). Patterns of early dietary exposures have implications for maternal and child weight outcomes Obesity (Silver Spring), 24(2), 430-8 | Study design, Intervention/exposure
2183 | Rosenbauer, J.,Herzig, P.,Giani, G. (2008). Early infant feeding and risk of type 1 diabetes mellitus-a nationwide population-based case-control study in pre-school children Diabetes Metab Res Rev, 24(3), 211-22 | Outcome
2184 | Rosenbauer, J.,Herzig, P.,Kaiser, P.,Giani, G. (2007). Early nutrition and risk of Type 1 diabetes mellitus--a nationwide case-control study in preschool children Exp Clin Endocrinol Diabetes, 115(8), 502-8 | Duplicate
2185 | Rosenberg, M. (1989). Breast-feeding and infant mortality in Norway 1860-1930 J Biosoc Sci, 21(3), 335-48 | Intervention/exposure
2186 | Rosenblatt, A.,Zarzar, P. (2002). The prevalence of early childhood caries in 12- to 36-month-old children in Recife, Brazil ASDC J Dent Child, 69(3), 319-24, 236 | Study design
2187 | Rosenblatt, W. H.,Brown, E. G. (1988). The nutritional status of breast-fed infants in a rural Peruvian community J Trop Pediatr, 34(6), 319-22 | Study design
2188 | Rossiter, J. C. (1993). Breast-feeding, the better option: getting the message across World Health Forum, 14(3), 316-8 | Study design
2189 | Rossiter, M. D.,Colapinto, C. K.,Khan, M. K.,McIsaac, J. L.,Williams, P. L.,Kirk, S. F.,Veugelers, P. J. (2015). Breast, Formula and Combination Feeding in Relation to Childhood Obesity in Nova Scotia, Canada Matern Child Health J, 19(9), 2048-56 | Study design
2190 | Rossiter, M. D.,Evers, S. E. (2013). Infant feeding practices and children’s weight status Can J Diet Pract Res, 74(3), 107-13 | Intervention/exposure, Outcome
2191 | Roszkowska, R.,Taranta-Janusz, K.,Tenderenda-Banasiuk, E.,Wasilewska, A. (2014). Increased circulating inflammatory markers may indicate that formula-fed children are at risk of atherosclerosis Acta Paediatr, 103(8), e354-8 | Study design, Outcome
2192 | Roszkowska, R.,Taranta-Janusz, K.,Tenderenda-Banasiuk, E.,Wasilewska, A. (2015). The effects of breastfeeding on serum asymmetric dimethylarginine levels and body composition in children Breastfeed Med, 10(#issue#), 38-44 | Study design
2193 | Roth DE (2016). Maternal postpartum high-dose vitamin D3 supplementation (6400 IU/day) or conventional infant vitamin D3 supplementation (400 IU/day) lead to similar vitamin D status of healthy exclusively/fully breastfeeding infants by 7 months of age Evid Based Med, 21(#issue#), 75 | Study design, Intervention/exposure
2194 | Rothenbacher, D.,Weyermann, M.,Beermann, C.,Brenner, H. (2005). Breastfeeding, soluble CD14 concentration in breast milk and risk of atopic dermatitis and asthma in early childhood: birth cohort study Clin Exp Allergy, 35(8), 1014-21 | Outcome
2195 | Rousseau, E. H.,Lescop, J. N.,Fontaine, S.,Lambert, J.,Roy, C. C. (1982). Influence of cultural and environmental factors on breast-feeding Can Med Assoc J, 127(8), 701-4 | Outcome
2196 | Routi, T.,Ronnemaa, T.,Viikari, J. S.,Leino, A.,Valimaki, I. A.,Simell, O. G. (1997). Tracking of serum lipoprotein (a) concentration and its contribution to serum cholesterol values in children from 7 to 36 months of age in the STRIP Baby Study. Special Turku Coronary Risk Factor Intervention Project for Babies Ann Med, 29(6), 541-7 | Intervention/exposure, Outcome
2197 | Rowland, M. G. (1985). The “why” and “when” of introducing food to infants: growth in young breast-fed infants and some nutritional implications Am J Clin Nutr, 41(2 Suppl), 459-63 | Study design
2198 | Rowntree, S.,Cogswell, J. J.,Platts-Mills, T. A.,Mitchell, E. B. (1985). Development of IgE and IgG antibodies to food and inhalant allergens in children at risk of allergic disease Arch Dis Child, 60(8), 727-35 | Size of study groups, Outcome
2199 | Rubin, D. H.,Leventhal, J. M.,Krasilnikoff, P. A.,Kuo, H. S.,Jekel, J. F.,Weile, B.,Levee, A.,Kurzon, M.,Berget, A. (1990). Relationship between infant feeding and infectious illness: a prospective study of infants during the first year of life Pediatrics, 85(4), 464-71 | Intervention/exposure
2200 | Rudant, J.,Lightfoot, T.,Urayama, K. Y.,Petridou, E.,Dockerty, J. D.,Magnani, C.,Milne, E.,Spector, L. G.,Ashton, L. J.,Dessypris, N.,Kang, A. Y.,Miller, M.,Rondelli, R.,Simpson, J.,Stiakaki, E.,Orsi, L.,Roman, E.,Metayer, C.,Infante-Rivard, C.,Clavel, J. (2015). Childhood acute lymphoblastic leukemia and indicators of early immune stimulation: A childhood leukemia international consortium study American Journal of Epidemiology, 181(8), 549-562 | Study design
2201 | Rudant, J.,Orsi, L.,Bonaventure, A.,Goujon-Bellec, S.,Baruchel, A.,Petit, A.,Bertrand, Y.,Nelken, B.,Pasquet, M.,Michel, G.,Saumet, L.,Chastagner, P.,Ducassou, S.,Reguerre, Y.,Hemon, D.,Clavel, J. (2015). ARID5B, IKZF1 and non-genetic factors in the etiology of childhood acute lymphoblastic leukemia: the ESCALE study PLoS One, 10(3), e0121348 | Intervention/exposure
2202 | Rudant, J.,Orsi, L.,Menegaux, F.,Petit, A.,Baruchel, A.,Bertrand, Y.,Lambilliotte, A.,Robert, A.,Michel, G.,Margueritte, G.,Tandonnet, J.,Mechinaud, F.,Bordigoni, P.,Hemon, D.,Clavel, J. (2010). Childhood acute leukemia, early common infections, and allergy: The ESCALE Study Am J Epidemiol, 172(9), 1015-27 | Outcome
2203 | Rudnicka, A. R.,Owen, C. G.,Richards, M.,Wadsworth, M. E.,Strachan, D. P. (2008). Effect of breastfeeding and sociodemographic factors on visual outcome in childhood and adolescence Am J Clin Nutr, 87(5), 1392-9 | Outcome
2204 | Rudnicka, A. R.,Owen, C. G.,Strachan, D. P. (2007). The effect of breastfeeding on cardiorespiratory risk factors in adult life Pediatrics, 119(5), e1107-15 | Intervention/exposure
2205 | Rudzeviciene, O.,Narkeviciute, I.,Eidukevicius, R. (2004). Lactose malabsorption in young Lithuanian children with atopic dermatitis Acta Paediatr, 93(4), 482-6 | Intervention/exposure
2206 | Ruijsbroek, A.,Wijga, A. H.,Kerkhof, M.,Koppelman, G. H.,Smit, H. A.,Droomers, M. (2011). The development of socio-economic health differences in childhood: results of the Dutch longitudinal PIAMA birth cohort BMC Public Health, 11(#issue#), 225 | Outcome
2207 | Ruiz-Charles, M. G.,Castillo-Rendón, R.,Bermúdez-Felizardo, F. (2002). Risk factors associated to bronchiolitis in infants less than two years of age Revista de Investigacion Clinica, 54(2), 125-132 | Language
2208 | Ruiz-Palacios, G. M.,Calva, J. J.,Pickering, L. K.,Lopez-Vidal, Y.,Volkow, P.,Pezzarossi, H.,West, M. S. (1990). Protection of breast-fed infants against Campylobacter diarrhea by antibodies in human milk J Pediatr, 116(5), 707-13 | Size of study groups
2209 | Rullo, V. E.,Arruda, L. K.,Cardoso, M. R.,Valente, V.,Zampolo, A. S.,Nobrega, F.,Naspitz, C. K.,Sole, D. (2009). Respiratory infection, exposure to mouse allergen and breastfeeding: role in recurrent wheezing in early life Int Arch Allergy Immunol, 150(2), 172-8 | Intervention/exposure
2210 | Rusconi, F.,Galassi, C.,Corbo, G. M.,Forastiere, F.,Biggeri, A.,Ciccone, G.,Renzoni, E.,Camerlengo, A.,Bugiani, M.,Dalmasso, P.,Faggiano, F.,Volante, T. F.,Magnani, C.,Natale, P.,Piccioni, P.,Bisanti, L.,Gianelle, V.,Sideri, S.,Piffer, S.,Filippetti, F.,Nava, E.,Biocca, M.,Canossa, E.,Cavalchi, B.,Cervino, D.,Cattani, S.,De’Munari, E.,Deserti, M.,Ferro, S.,Fortezza, F.,Frigo, F.,Martini, M.,Mazzali, P.,Paterlini, L.,Sogni, R.,Zanini, M.,Romagna, E.,Chellini, E.,Agati, L.,Barletta, E.,Bini, G.,Bini, M.,Chetoni, L.,Grechi, D.,Costantini, A. S.,Sestini, P.,Viegi, G.,Agabiti, N.,Dell’Orco, V.,Mallone, S.,Micera, C.,Palermo, P.,Pallotti, G.,Piras, C.,Pistelli, R.,Salera, E.,Argentini, D.,Chiarucci, G. (1999). Risk factors for early, persistent, and late-onset wheezing in young children American Journal of Respiratory and Critical Care Medicine, 160(5 I), 1617-1622 | Study design
2211 | Rush, E. C.,Paterson, J.,Obolonkin, V. V.,Puniani, K. (2008). Application of the 2006 WHO growth standard from birth to 4 years to Pacific Island children Int J Obes (Lond), 32(3), 567-72 | Intervention/exposure
2212 | Rush, E.,Gao, W.,Funaki-Tahifote, M.,Ngamata, R.,Matenga-Smith, T.,Cassidy, M.,Paterson, J. (2010). Birth weight and growth trajectory to six years in Pacific children Int J Pediatr Obes, 5(2), 192-9 | Intervention/exposure
2213 | Russo, R. M.,Patel, R.,Laude, T. A.,Rajkumar, S. V.,Gururaj, V. J. (1981). Infant feeding practices by ethno-cultural grouping J Med Soc N J, 78(11), 737-40 | Study design, Outcome
2214 | Rutishauser, I. H.,McKay, H. M.,Wahlqvist, M. L. (1982). Does breast feeding have nutritional advantages over bottle feeding? Aust Fam Physician, 11(4), 249-50, 252-3, 255-6 | Study design
2215 | Ruuska, T. (1992). Occurrence of acute diarrhea in atopic and nonatopic infants: the role of prolonged breast-feeding J Pediatr Gastroenterol Nutr, 14(1), 27-33 | Outcome
2216 | Ruuska, T.,Vesikari, T. (1991). A prospective study of acute diarrhoea in Finnish children from birth to 2 1/2 years of age Acta Paediatr Scand, 80(5), 500-7 | Size of study groups
2217 | Ruys, J. H.,de Jonge, G. A.,Brand, R.,Engelberts, A. C.,Semmekrot, B. A. (2007). Bed-sharing in the first four months of life: a risk factor for sudden infant death Acta Paediatr, 96(10), 1399-403 | Study design
2218 | Rylander, E.,Pershagen, G.,Eriksson, M.,Nordvall, L. (1993). Parental smoking and other risk factors for wheezing bronchitis in children Eur J Epidemiol, 9(5), 517-26 | Intervention/exposure
2219 | Rzehak, P.,Sausenthaler, S.,Koletzko, S.,Bauer, C. P.,Schaaf, B.,von Berg, A.,Berdel, D.,Borte, M.,Herbarth, O.,Kramer, U.,Fenske, N.,Wichmann, H. E.,Heinrich, J. (2009). Period-specific growth, overweight and modification by breastfeeding in the GINI and LISA birth cohorts up to age 6 years Eur J Epidemiol, 24(8), 449-67 | Intervention/exposure
2220 | Rzehak, P.,Sausenthaler, S.,Koletzko, S.,Reinhardt, D.,von Berg, A.,Kramer, U.,Berdel, D.,Bollrath, C.,Grubl, A.,Bauer, C. P.,Wichmann, H. E.,Heinrich, J. (2009). Short- and long-term effects of feeding hydrolyzed protein infant formulas on growth at < or = 6 y of age: results from the German Infant Nutritional Intervention Study Am J Clin Nutr, 89(6), 1846-56 | Intervention/exposure
2221 | Saarinen, K. M.,Juntunen-Backman, K.,Jarvenpaa, A. L.,Klemetti, P.,Kuitunen, P.,Lope, L.,Renlund, M.,Siivola, M.,Vaarala, O.,Savilahti, E. (2000). Breast-feeding and the development of cows’ milk protein allergy Adv Exp Med Biol, 478(#issue#), 121-30 | Intervention/exposure, Publication status
2222 | Saarinen, K. M.,Juntunen-Backman, K.,Jarvenpaa, A. L.,Kuitunen, P.,Lope, L.,Renlund, M.,Siivola, M.,Savilahti, E. (1999). Supplementary feeding in maternity hospitals and the risk of cow’s milk allergy: A prospective study of 6209 infants J Allergy Clin Immunol, 104(2 Pt 1), 457-61 | Study design, Intervention/exposure
2223 | Saarinen, K. M.,Savilahti, E. (2000). Infant feeding patterns affect the subsequent immunological features in cow’s milk allergy Clin Exp Allergy, 30(3), 400-6 | Participant health, Outcomes
2224 | Saarinen, U. M. (1982). Prolonged breast feeding as prophylaxis for recurrent otitis media Acta Paediatr Scand, 71(4), 567-71 | Intervention/exposure
2225 | Saarinen, U. M.,Kajosaari, M. (1995). Breastfeeding as prophylaxis against atopic disease: prospective follow-up study until 17 years old Lancet, 346(8982), 1065-9 | Intervention/exposure
2226 | Saarinen, U. M.,Kajosaari, M.,Backman, A. (1982). Birch pollen allergy in children. Role of milk feeding during the first birch season of life Allergy, 37(5), 345-50 | Outcome
2227 | Sabanayagam, C.,Shankar, A.,Chong, Y. S.,Wong, T. Y.,Saw, S. M. (2009). Breast-feeding and overweight in Singapore school children Pediatr Int, 51(5), 650-6 | Study design
2228 | Sabuncuoglu, O.,Orengul, C.,Bikmazer, A.,Kaynar, S. Y. (2014). Breastfeeding and parafunctional oral habits in children with and without attention-deficit/hyperactivity disorder Breastfeed Med, 9(5), 244-50 | Outcome
2229 | Sacker, A.,Kelly, Y.,Iacovou, M.,Cable, N.,Bartley, M. (2013). Breast feeding and intergenerational social mobility: what are the mechanisms? Arch Dis Child, 98(9), 666-71 | Intervention/exposure, Outcome
2230 | Sacker, A.,Quigley, M. A.,Kelly, Y. J. (2006). Breastfeeding and developmental delay: findings from the millennium cohort study Pediatrics, 118(3), e682-9 | Study design
2231 | Sadauskaite-Kuehne, V.,Ludvigsson, J.,Padaiga, Z.,Jasinskiene, E.,Samuelsson, U. (2004). Longer breastfeeding is an independent protective factor against development of type 1 diabetes mellitus in childhood Diabetes Metab Res Rev, 20(2), 150-7 | Outcome
2232 | Sadeharju, K.,Knip, M.,Virtanen, S. M.,Savilahti, E.,Tauriainen, S.,Koskela, P.,Akerblom, H. K.,Hyoty, H. (2007). Maternal antibodies in breast milk protect the child from enterovirus infections Pediatrics, 119(5), 941-6 | Outcome
2233 | Saeed, M.,Waseem, Q.,Ali Shair, Q.,Omonogun, B. A.,Al Husein, A. (2008). Vitamin D deficiency rickets in Maternity and Children’s Hospital, Najran, Saudi Arabia Pakistan Paediatric Journal, 32(3), 145-148 | Publication status
2234 | Sahakyan, A.,Armenian, H. K.,Breitscheidel, L.,Thompson, M. E.,Enokyan, G. (2006). Feeding practices of babies and the development of atopic dermatitis in children after 12 months of age in Armenia: Is there a signal? European Journal of Epidemiology, 21(9), 723-725 | Intervention/exposure
2235 | Sahin, F.,Camurdan, A. D.,Camurdan, M. O.,Olmez, A.,Oznurhan, F.,Beyazova, U. (2008). Factors affecting the timing of teething in healthy Turkish infants: a prospective cohort study Int J Paediatr Dent, 18(4), 262-6 | Intervention/exposure, Outcome
2236 | Sajjad, A.,Tharner, A.,Kiefte-de Jong, J. C.,Jaddoe, V. V.,Hofman, A.,Verhulst, F. C.,Franco, O. H.,Tiemeier, H.,Roza, S. J. (2015). Breastfeeding duration and non-verbal IQ in children J Epidemiol Community Health, 69(8), 775-81 | Outcome
2237 | Saki Malehi, A.,Hajizadeh, E.,Ahmadi, K.,Kholdi, N. (2014). Modeling the recurrent failure to thrive in less than two-year children: recurrent events survival analysis J Res Health Sci, 14(1), 96-9 | Outcome
2238 | Salah, M.,Abdel-Aziz, M.,Al-Farok, A.,Jebrini, A. (2013). Recurrent acute otitis media in infants: analysis of risk factors Int J Pediatr Otorhinolaryngol, 77(10), 1665-9 | Non-human sample, Participant health
2239 | Salariya, E. M. (1993). Breast versus bottle feeding Nutr Health, 9(1), 33-6 | Study design
2240 | Salariya, E. M.,Easton, P. M.,Cater, J. I. (1979). Early and often for best results. RCT on breast feeding Nursing mirror, 148(#issue#), 15-7 | Size of study groups, Outcome
2241 | Salariya, E. M.,Robertson, C. M. (1993). Relationships between baby feeding types and patterns, gut transit time of meconium and the incidence of neonatal jaundice Midwifery, 9(4), 235-42 | Outcome
2242 | Sala-Vila, A.,Campoy, C.,Castellote, A. I.,Garrido, F. J.,Rivero, M.,Rodríguez-Palmero, M.,López-Sabater, M. C. (2006). Influence of dietary source of docosahexaenoic and arachidonic acids on their incorporation into membrane phospholipids of red blood cells in term infants Prostaglandins Leukotrienes and Essential Fatty Acids, 74(2), 143-148 | Size of study groups
2243 | Sala-Vila, A.,Castellote, A. I.,Campoy, C.,Rivero, M.,Rodriguez-Palmero, M.,Lopez-Sabater, M. C. (2004). The source of long-chain PUFA in formula supplements does not affect the fatty acid composition of plasma lipids in full-term infants J Nutr, 134(4), 868-73 | Size of study groups
2244 | Salazar, J. C.,Daly, K. A.,Giebink, G. S.,Lindgren, B. R.,Liebeler, C. L.,Meland, M.,Le, C. T. (1997). Low cord blood pneumococcal immunoglobulin G (IgG) antibodies predict early onset acute otitis media in infancy Am J Epidemiol, 145(11), 1048-56 | Intervention/exposure
2245 | Salmenpera, L.,Perheentupa, J.,Siimes, M. A. (1985). Exclusively breast-fed healthy infants grow slower than reference infants Pediatr Res, 19(3), 307-12 | Intervention/exposure
2246 | Salmenpera, L.,Perheentupa, J.,Siimes, M. A.,Adrian, T. E.,Bloom, S. R.,Aynsley-Green, A. (1988). Effects of feeding regimen on blood glucose levels and plasma concentrations of pancreatic hormones and gut regulatory peptides at 9 months of age: comparison between infants fed with milk formula and infants exclusively breast-fed from birth J Pediatr Gastroenterol Nutr, 7(5), 651-6 | Size of study groups
2247 | Salmon, T. G., Jr. (1997). Early childhood caries: a private practitioner’s perspective Pediatr Dent, 19(1), 63-4 | Study design
2248 | Salo, P.,Viikari, J.,Hamalainen, M.,Lapinleimu, H.,Routi, T.,Ronnemaa, T.,Seppanen, R.,Jokinen, E.,Valimaki, I.,Simell, O. (1999). Serum cholesterol ester fatty acids in 7- and 13-month-old children in a prospective randomized trial of a low-saturated fat, low-cholesterol diet: the STRIP baby project. Special Turku coronary Risk factor Intervention Project for children Acta Paediatr, 88(5), 505-12 | Intervention/exposure
2249 | Salo, P.,Viikari, J.,Ronnemaa, T.,Hamalainen, M.,Jokinen, E.,Valimaki, I.,Simell, O. (1997). Milk type during mixed feeding: contribution to serum cholesterol ester fatty acids in late infancy J Pediatr, 130(1), 110-6 | Intervention/exposure
2250 | Salsberry, P. J.,Reagan, P. B. (2005). Dynamics of early childhood overweight Pediatrics, 116(6), 1329-38 | Outcome
2251 | Salsberry, P. J.,Reagan, P. B. (2007). Taking the long view: the prenatal environment and early adolescent overweight Res Nurs Health, 30(3), 297-307 | Outcome
2252 | Salvioli, G. P.,Faldella, G.,Alessandroni, R.,Lanari, M.,Di Turi, R. P. (1995). Iron nutrition and iron status changes in Italian infants in the last decade Ann Ist Super Sanita, 31(4), 455-9 | Study design
2253 | Samarakkody, D.,Fernando, D.,McClure, R.,Perera, H.,De Silva, H. (2012). Prevalence of externalizing behavior problems in Sri Lankan preschool children: birth, childhood, and sociodemographic risk factors Soc Psychiatry Psychiatr Epidemiol, 47(5), 757-62 | Study design
2254 | Samuelsson, U.,Johansson, C.,Ludvigsson, J. (1993). Breast-feeding seems to play a marginal role in the prevention of insulin-dependent diabetes mellitus Diabetes Res Clin Pract, 19(3), 203-10 | Outcome
2255 | Samuelsson, U.,Ludvigsson, J. (2001). Seasonal variation of birth month and breastfeeding in children with diabetes mellitus J Pediatr Endocrinol Metab, 14(1), 43-6 | Outcome
2256 | Sanchez-Molins, M.,Grau Carbo, J.,Lischeid Gaig, C.,Ustrell Torrent, J. M. (2010). Comparative study of the craniofacial growth depending on the type of lactation received Eur J Paediatr Dent, 11(2), 87-92 | Size of study groups, Intervention/exposure
2257 | Sánchez-Uribe, E.,Esparza-Aguilar, M.,Gastañaduy, P. A.,Desai, R.,Patel, M.,Richardson, V. (2013). Risk factors associated with rotavirus gastroenteritis during a community outbreak in Chiapas, Mexico during the postvaccination Era Journal of the Pediatric Infectious Diseases Society, 2(1), 15-20 | Intervention/exposure
2258 | Sanchez-Valverde, F.,Gil, F.,Martinez, D.,Fernandez, B.,Aznal, E.,Oscoz, M.,Olivera, J. E. (2009). The impact of caesarean delivery and type of feeding on cow’s milk allergy in infants and subsequent development of allergic march in childhood Allergy, 64(6), 884-9 | Participant health
2259 | Sanders TA,Reddy S (1992). The influence of a vegetarian diet on the fatty acid composition of human milk and the essential fatty acid status of the infant J Pediatr, 120(#issue#), S71-7 | Size of study groups
2260 | Sandini, U.,Kukkonen, A. K.,Poussa, T.,Sandini, L.,Savilahti, E.,Kuitunen, M. (2011). Protective and risk factors for allergic diseases in high-risk children at the ages of two and five years Int Arch Allergy Immunol, 156(3), 339-48 | Outcome
2261 | Sandstrom, O.,Lonnerdal, B.,Graverholt, G.,Hernell, O. (2008). Effects of alpha-lactalbumin-enriched formula containing different concentrations of glycomacropeptide on infant nutrition Am J Clin Nutr, 87(4), 921-8 | Size of study groups
2262 | Sanger, R. G.,Bystrom, E. B. (1982). Breast feeding: does it affect oral facial growth? Dent Hyg (Chic), 56(6), 44-7 | Study design
2263 | Sangun, O.,Dundar, B.,Kosker, M.,Pirgon, O.,Dundar, N. (2011). Prevalence of metabolic syndrome in obese children and adolescents using three different criteria and evaluation of risk factors J Clin Res Pediatr Endocrinol, 3(2), 70-6 | Outcome
2264 | Sanin, L. H.,Gonzalez-Cossio, T.,Romieu, I.,Peterson, K. E.,Ruiz, S.,Palazuelos, E.,Hernandez-Avila, M.,Hu, H. (2001). Effect of maternal lead burden on infant weight and weight gain at one month of age among breastfed infants Pediatrics, 107(5), 1016-23 | Study design
2265 | Sanjurjo, P.,Rodriguez-Alarcon, J.,Rodriguez-Soriano, J. (1988). Plasma fatty acid composition during the first week of life following feeding with human milk or formula Acta Paediatr Scand, 77(2), 202-6 | Size of study groups
2266 | Santorelli, G.,Fairley, L.,Petherick, E. S.,Cabieses, B.,Sahota, P. (2014). Ethnic differences in infant feeding practices and their relationship with BMI at 3 years of age - results from the Born in Bradford birth cohort study Br J Nutr, 111(10), 1891-7 | Outcome
2267 | Santos, C. A.,Strina, A.,Amorim, L. D.,Genser, B.,Assis, A. M.,Prado, M. S.,Barreto, M. L. (2012). Individual and contextual determinants of the duration of diarrhoeal episodes in preschool children: a longitudinal study in an urban setting Epidemiol Infect, 140(4), 689-96 | Participant health
2268 | Santos, I. S.,Matijasevich, A.,Assuncao, M. C.,Valle, N. C.,Horta, B. L.,Goncalves, H. D.,Gigante, D. P.,Martines, J. C.,Pelto, G.,Victora, C. G. (2015). Promotion of Weight Gain in Early Childhood Does Not Increase Metabolic Risk in Adolescents: A 15-Year Follow-Up of a Cluster-Randomized Controlled Trial J Nutr, 145(12), 2749-55 | Intervention/exposure
2269 | Santos, I. S.,Matijasevich, A.,Barros, A. J.,Albernaz, E. P.,Domingues, M. R.,Valle, N. C.,Malta, D. C.,Gorgot, L. R.,Barros, F. C. (2011). Avoidable deaths in the first four years of life among children in the 2004 Pelotas (Brazil) birth cohort study Cad Saude Publica, 27 Suppl 2(#issue#), S185-97 | Outcome
2270 | Santos, I.,Victora, C. G.,Martines, J.,Goncalves, H.,Gigante, D. P.,Valle, N. J.,Pelto, G. (2001). Nutrition counseling increases weight gain among Brazilian children J Nutr, 131(11), 2866-73 | Intervention/exposure
2271 | Sarasa Munoz, N. L. (2013). Mother’s milk still best--and we must do better MEDICC Rev, 15(1), 48 | Study design
2272 | Sariachvili, M.,Droste, J.,Dom, S.,Wieringa, M.,Vellinga, A.,Hagendorens, M.,Bridts, C.,Stevens, W.,Sprundel, M. V.,Desager, K.,Weyler, J. (2007). Is breast feeding a risk factor for eczema during the first year of life? Pediatr Allergy Immunol, 18(5), 410-7 | Outcome
2273 | Sartorius, N. (2007). Learning how to speak Croat Med J, 48(2), 259-60 | Study design
2274 | Sasai, K.,Furukawa, S.,Kaneko, K.,Yabuta, K.,Baba, M. (1994). Fecal IgE levels in infants at 1 month of age as indicator of atopic disease Allergy, 49(9), 791-4 | Study design, Size of study groups
2275 | Sassen, M. L.,Brand, R.,Grote, J. J. (1994). Breast-feeding and acute otitis media Am J Otolaryngol, 15(5), 351-7 | Outcome
2276 | Sastry, N.,Burgard, S. (2011). Changes in Diarrheal Disease and Treatment Among Brazilian Children from 1986 to 1996 Popul Res Policy Rev, 30(1), 81-100 | Study design
2277 | Saukkonen, T.,Virtanen, S. M.,Karppinen, M.,Reijonen, H.,Ilonen, J.,Räsänen, L., (1998). Significance of cow’s milk protein antibodies as risk factor for childhood IDDM: Interactions with dietary cow’s milk intake and HLA-DQB1 genotype Diabetologia, 41(1), 72-78 | Redundant data with another study
2278 | Savilahti, E.,Saarinen, K. M. (2009). Early infant feeding and type 1 diabetes Eur J Nutr, 48(4), 243-9 | Outcome
2279 | Savilahti, E.,Salmenpera, L.,Tainio, V. M.,Halme, H.,Perheentupa, J.,Siimes, M. A. (1987). Prolonged exclusive breast-feeding results in low serum concentrations of immunoglobulin G, A and M Acta Paediatr Scand, 76(1), 1-6 | Intervention/exposure, Outcome
2280 | Savilahti, E.,Siltanen, M.,Kajosaari, M.,Vaarala, O.,Saarinen, K. M. (2005). IgA antibodies, TGF-beta1 and -beta2, and soluble CD14 in the colostrum and development of atopy by age 4 Pediatr Res, 58(6), 1300-5 | Outcome
2281 | Savilahti, E.,Tainio, V. M.,Salmenpera, L.,Arjomaa, P.,Kallio, M.,Perheentupa, J.,Siimes, M. A. (1991). Levels of IgA and cow milk antibodies in breast milk vs. the development of atopy in children. Low colostral IgA associated with cow milk allergy Adv Exp Med Biol, 310(#issue#), 417-25 | Intervention/exposure
2282 | Savilahti, E.,Tainio, V. M.,Salmenpera, L.,Siimes, M. A.,Perheentupa, J. (1987). Prolonged exclusive breast feeding and heredity as determinants in infantile atopy Arch Dis Child, 62(3), 269-73 | Outcome
2283 | Savino, F.,Liguori, S. A.,Benetti, S.,Sorrenti, M.,Fissore, M. F.,Cordero di Montezemolo, L. (2013). High serum leptin levels in infancy can potentially predict obesity in childhood, especially in formula-fed infants Acta Paediatr, 102(10), e455-9 | Outcome
2284 | Savino, F.,Maccario, S.,Cresi, F.,Grasso, G.,Oggero, R.,Silvestro, L.,Mussa, G. C. (2004). Bioimpedance vector analysis in breastfed and formula-fed infants in the first six months of life Adv Exp Med Biol, 554(#issue#), 501-4 | Size of study groups
2285 | Savino, F.,Oggero, R.,Prino, A.,Mostert, M. (1997). Hypoantigenic (HA) milk formula and blood cholesterol level in infants at 3 months of age Acta Paediatr, 86(9), 1003-5 | Outcome
2286 | Savino, F.,Serraino, P.,Prino, A.,Oggero, R.,Bretto, R.,Mostert, M. (2000). Arachidonic (AA) and docosahexaenoic (DHA) acid content in healthy infants fed with an HA milk formula supplemented with LCPUFA and in breast fed infants Adv Exp Med Biol, 478(#issue#), 411-2 | Study design, Size of study groups
2287 | Savion I,Savion I (2007). Nursing of malnourished children with emphasis on polyunsaturated fatty acids Appl Nurs Res, 20(#issue#), 140-5 | Intervention/exposure, Study design
2288 | Sawchuk, L. A.,Burke, S. D. (2000). Mortality in an early Ontario community: Belleville 1876-1885 Urban Hist Rev, 29(1), 33-47 | Study design
2289 | Sawley, L. (1985). Bottle feeding Nurs Mirror, 160(3), 31-3 | Study design
2290 | Sawley, L. (1985). Breast is best Nurs Mirror, 160(2), 15-9 | Study design
2291 | Sawley, L. (1989). Infant feeding Nursing (Lond), 3(39), 18-23 | Study design
2292 | Say, G. N.,Karabekiroglu, K.,Babadagi, Z.,Yuce, M. (2015). Maternal stress and perinatal features in autism & attention deficit/hyperactivity disorder Pediatr Int, #volume#(#issue#), #Pages# | Outcome
2293 | Sayegh, A.,Dini, E. L.,Holt, R. D.,Bedi, R. (2002). Caries prevalence and patterns and their relationship to social class, infant feeding and oral hygiene in 4-5-year-old children in Amman, Jordan Community Dent Health, 19(3), 144-51 | Study design
2294 | Sayegh, A.,Dini, E. L.,Holt, R. D.,Bedi, R. (2005). Oral health, sociodemographic factors, dietary and oral hygiene practices in Jordanian children J Dent, 33(5), 379-88 | Study design
2295 | Sayyed, T.,Kandil, M.,Bashir, O.,Alnaser, H. (2014). The relationship between term pre-eclampsia and the risk of early childhood caries J Matern Fetal Neonatal Med, 27(1), 62-5 | Size of study groups
2296 | Scaglioni, S.,Agostoni, C.,Notaris, R. D.,Radaelli, G.,Radice, N.,Valenti, M.,Giovannini, M.,Riva, E. (2000). Early macronutrient intake and overweight at five years of age Int J Obes Relat Metab Disord, 24(6), 777-81 | Outcome
2297 | Scalabrin, D.,Mitmesser, S.,Birch, E.,Khoury, J.,Bean, J.,Harris, C.,Berseth, C. (2011). Lower incidence and less recurrence of allergic manifestations is observed in children who received docosahexaenoic acid/arachidonic acid in infancy via breast milk or supplemented formula Allergy: European Journal of Allergy and Clinical Immunology. Conference: 30th Congress of the European Academy of Allergy and Clinical Immunology Istanbul Turkey. Conference Start: 20110611 Conference End: 20110615. Conference Publication: (var.pagings), 66(94), 711 | Publication status
2298 | Scariati, P. D.,Grummer-Strawn, L. M.,Fein, S. B. (1997). A longitudinal analysis of infant morbidity and the extent of breastfeeding in the United States Pediatrics, 99(6), E5 | Outcome
2299 | Scariati, P. D.,Grummer-Strawn, L. M.,Fein, S. B.,Yip, R. (1997). Risk of diarrhea related to iron content of infant formula: lack of evidence to support the use of low-iron formula as a supplement for breastfed infants Pediatrics, 99(3), E2 | Intervention/exposure
2300 | Scarlett D,Cargill M,Lyn-Sue J,Richardson S,McCaw-Binns A (1996). Breastfeeding prevalence among six-week-old infants at University Hospital of the West Indies West Indian Med J, 45(#issue#), 14-7 | Study design
2301 | Scerri, C.,Savona-Ventura, C. (2010). Early metabolic imprinting as a determinant of childhood obesity International Journal of Diabetes Mellitus, 2(3), 175-178 | Study design
2302 | Schach, B.,Haight, M. (2002). Colic and food allergy in the breastfed infant: is it possible for an exclusively breastfed infant to suffer from food allergy? J Hum Lact, 18(1), 50-2 | Study design
2303 | Schack-Nielsen, L.,Michaelsen, K. F.,Mortensen, E. L.,Sorensen, T. I.,Reinisch, J. M. (2004). Is duration of breastfeeding influencing the risk of obesity in adult males? Adv Exp Med Biol, 554(#issue#), 383-5 | Study design
2304 | Schack-Nielsen, L.,Molgaard, C.,Larsen, D.,Martyn, C.,Michaelsen, K. F. (2004). Arterial compliance in 10-year-old children in relation to breastfeeding Adv Exp Med Biol, 554(#issue#), 391-3 | Duplicate
2305 | Schack-Nielsen, L.,Molgaard, C.,Larsen, D.,Martyn, C.,Michaelsen, K. F. (2005). Arterial stiffness in 10-year-old children: current and early determinants Br J Nutr, 94(6), 1004-11 | Outcome
2306 | Schack-Nielsen, L.,Sorensen, TIa,Mortensen, E. L.,Michaelsen, K. F. (2010). Late introduction of complementary feeding, rather than duration of breastfeeding, may protect against adult overweight Am J Clin Nutr, 91(3), 619-27 | Outcome
2307 | Schaefer-Graf, U. M.,Hartmann, R.,Pawliczak, J.,Passow, D.,Abou-Dakn, M.,Vetter, K.,Kordonouri, O. (2006). Association of breast-feeding and early childhood overweight in children from mothers with gestational diabetes mellitus Diabetes Care, 29(5), 1105-7 | Study design
2308 | Scheer, B. (1985). Caries in children--the dietary factor Middle East Dent Oral Health, #volume#(3), 20-2 | Study design
2309 | Scheiwe, A.,Hardy, R.,Watt, R. G. (2010). Four-year follow-up of a randomized controlled trial of a social support intervention on infant feeding practices Matern Child Nutr, 6(4), 328-37 | Study design, Intervention/exposure
2310 | Schellscheidt, J.,Ott, A.,Jorch, G. (1997). Epidemiological features of sudden infant death after a German intervention campaign in 1992 Eur J Pediatr, 156(8), 655-60 | Outcome
2311 | Scherdel, P.,Botton, J.,Rolland-Cachera, M. F.,Leger, J.,Pele, F.,Ancel, P. Y.,Simon, C.,Castetbon, K.,Salanave, B.,Thibault, H.,Lioret, S.,Peneau, S.,Gusto, G.,Charles, M. A.,Heude, B. (2015). Should the WHO growth charts be used in France? PLoS One, 10(3), e0120806 | Study design, Intervention/exposure
2312 | Schilithz, A. O.,Kale, P. L.,Gama, S. G.,Nobre, F. F. (2014). Risk groups in children under six months of age using self-organizing maps Comput Methods Programs Biomed, 115(1), 1-10 | Study design, Intervention/exposure
2313 | Schluter, P. J.,Durward, C.,Cartwright, S.,Paterson, J. (2007). Maternal self-report of oral health in 4-year-old Pacific children from South Auckland, New Zealand: findings from the Pacific Islands Families Study J Public Health Dent, 67(2), 69-77 | Outcome
2314 | Schluter, P. J.,Ford, R. P.,Mitchell, E. A.,Taylor, B. J. (1998). Residential mobility and sudden infant death syndrome J Paediatr Child Health, 34(5), 432-7 | Intervention/exposure
2315 | Schluter, P. J.,Paterson, J.,Percival, T. (2007). Infant care practices associated with sudden infant death syndrome: findings from the Pacific Islands Families study J Paediatr Child Health, 43(5), 388-93 | Study design
2316 | Schmidt BJ (1983). Breast-feeding and infant morbidity and mortality in developing countries J Pediatr Gastroenterol Nutr, 2 Suppl 1(#issue#), S127-30 | Study design
2317 | Schmidt, M. E.,Rich, M.,Rifas-Shiman, S. L.,Oken, E.,Taveras, E. M. (2009). Television viewing in infancy and child cognition at 3 years of age in a US cohort Pediatrics, 123(3), e370-5 | Intervention/exposure
2318 | Schmidt, R. J.,Tancredi, D. J.,Krakowiak, P.,Hansen, R. L.,Ozonoff, S. (2014). Maternal intake of supplemental iron and risk of autism spectrum disorder Am J Epidemiol, 180(9), 890-900 | Intervention/exposure, Outcome
2319 | Schmitt, J.,Romanos, M. (2012). Prenatal and perinatal risk factors for attention-deficit/hyperactivity disorder Arch Pediatr Adolesc Med, 166(11), 1074-5 | Study design
2320 | Schnitzer, M. E.,Moodie, E. E.,Platt, R. W. (2013). Targeted maximum likelihood estimation for marginal time-dependent treatment effects under density misspecification Biostatistics, 14(1), 1-14 | Outcome
2321 | Schnitzer, M. E.,van der Laan, M. J.,Moodie, E. E.,Platt, R. W. (2014). EFFECT OF BREASTFEEDING ON GASTROINTESTINAL INFECTION IN INFANTS: A TARGETED MAXIMUM LIKELIHOOD APPROACH FOR CLUSTERED LONGITUDINAL DATA Ann Appl Stat, 8(2), 703-725 | Outcome
2322 | Schoen, S.,Sichert-Hellert, W.,Kersting, M. (2009). Validation of energy requirement equations for estimation of breast milk consumption in infants Public Health Nutr, 12(12), 2309-16 | Outcome
2323 | Schoetzau, A.,Filipiak-Pittroff, B.,Franke, K.,Koletzko, S.,Von Berg, A.,Gruebl, A.,Bauer, C. P.,Berdel, D.,Reinhardt, D.,Wichmann, H. E. (2002). Effect of exclusive breast-feeding and early solid food avoidance on the incidence of atopic dermatitis in high-risk infants at 1 year of age Pediatr Allergy Immunol, 13(4), 234-42 | Intervention/exposure
2324 | Scholtens, S.,Brunekreef, B.,Smit, H. A.,Gast, G. C.,Hoekstra, M. O.,de Jongste, J. C.,Postma, D. S.,Gerritsen, J.,Seidell, J. C.,Wijga, A. H. (2008). Do differences in childhood diet explain the reduced overweight risk in breastfed children? Obesity (Silver Spring), 16(11), 2498-503 | Outcome
2325 | Scholtens, S.,Gehring, U.,Brunekreef, B.,Smit, H. A.,de Jongste, J. C.,Kerkhof, M.,Gerritsen, J.,Wijga, A. H. (2007). Breastfeeding, weight gain in infancy, and overweight at seven years of age: the prevention and incidence of asthma and mite allergy birth cohort study Am J Epidemiol, 165(8), 919-26 | Outcome
2326 | Scholtens, S.,Wijga, A. H.,Brunekreef, B.,Kerkhof, M.,Hoekstra, M. O.,Gerritsen, J.,Aalberse, R.,de Jongste, J. C.,Smit, H. A. (2009). Breast feeding, parental allergy and asthma in children followed for 8 years. The PIAMA birth cohort study Thorax, 64(7), 604-9 | Outcome
2327 | Schraw, J. M.,Dong, Y. Q.,Okcu, M. F.,Scheurer, M. E.,Forman, M. R. (2014). Do longer formula feeding and later introduction of solids increase risk for pediatric acute lymphoblastic leukemia? Cancer Causes and Control, 25(1), 73-80 | Outcome
2328 | Schroeder, N.,Rushovich, B.,Bartlett, E.,Sharma, S.,Gittelsohn, J.,Caballero, B. (2015). Early Obesity Prevention: A Randomized Trial of a Practice-Based Intervention in 0-24-Month Infants J Obes, 2015(#issue#), 795859 | Intervention/exposure
2329 | Schuz, J.,Kaletsch, U.,Meinert, R.,Kaatsch, P.,Michaelis, J. (1999). Association of childhood leukaemia with factors related to the immune system Br J Cancer, 80(3-4), 585-90 | Outcome
2330 | Schwartz, J.,Drossard, C.,Dube, K.,Kannenberg, F.,Kunz, C.,Kalhoff, H.,Kersting, M. (2010). Dietary intake and plasma concentrations of PUFA and LC-PUFA in breastfed and formula fed infants under real-life conditions Eur J Nutr, 49(3), 189-95 | Size of study groups
2331 | Schwartz, R.,Vigo, A.,de Oliveira, L. D.,Justo Giugliani, E. R. (2015). The Effect of a Pro-Breastfeeding and Healthy Complementary Feeding Intervention Targeting Adolescent Mothers and Grandmothers on Growth and Prevalence of Overweight of Preschool Children PLoS One, 10(7), e0131884 | Intervention/exposure
2332 | Schwartzbaum, J. A.,George, S. L.,Pratt, C. B.,Davis, B. (1991). An exploratory study of environmental and medical factors potentially related to childhood cancer Med Pediatr Oncol, 19(2), 115-21 | Study design
2333 | Schwarz, T. (1990). Bottle or breast. The first big decision Nurs Times, 86(35), 63-5 | Study design
2334 | Schwarze, C. E.,Hellhammer, D. H.,Stroehle, V.,Lieb, K.,Mobascher, A. (2015). Lack of Breastfeeding: A Potential Risk Factor in the Multifactorial Genesis of Borderline Personality Disorder and Impaired Maternal Bonding J Pers Disord, 29(5), 610-26 | Study design, Outcome
2335 | Schweitzer, F. C.,Prager, T. C.,Zou, Y.,Ruiz, R. S.,Chen, H.,Anderson, R. E.,Jensen, C. L.,Heird, W. C. (1995). Effect of 18:3ù3 intake on pattern visual evoked potentials in term infants Iovs, 36(#issue#), ARVO Abstract 235 | Publication status
2336 | Sclavos S,Porter S,Kim Seow W (1988). Future caries development in children with nursing bottle caries J Pedod, 13(#issue#), 1-10 | Intervention/exposure
2337 | Scott, D. T.,Janowsky, J. S.,Carroll, R. E.,Taylor, J. A.,Auestad, N.,Montalto, M. B. (1998). Formula supplementation with long-chain polyunsaturated fatty acids: are there developmental benefits? Pediatrics, 102(5), E59 | Outcome
2338 | Scott, F. W.,Kolb, H. (1998). Dietary intervention for diabetes prevention in the neonate Diabetes Metab Rev, 14(1), 106 | Study design
2339 | Scott, J. A.,Ng, S. Y.,Cobiac, L. (2012). The relationship between breastfeeding and weight status in a national sample of Australian children and adolescents BMC Public Health, 12(#issue#), 107 | Study design
2340 | Scott, M.,Roberts, G.,Kurukulaaratchy, R. J.,Matthews, S.,Nove, A.,Arshad, S. H. (2012). Multifaceted allergen avoidance during infancy reduces asthma during childhood with the effect persisting until age 18 years Thorax, 67(12), 1046-51 | Intervention/exposure
2341 | Seach, K. A.,Dharmage, S. C.,Lowe, A. J.,Dixon, J. B. (2010). Delayed introduction of solid feeding reduces child overweight and obesity at 10 years Int J Obes (Lond), 34(10), 1475-9 | Outcome
2342 | Seal, N.,Broome, M. E. (2013). Prepregnancy Body Mass Index and Feeding Practices in Relation to Infants’ Growth J Nurse Pract, 9(5), #Pages# | Study design
2343 | Sears, M. R.,Greene, J. M.,Willan, A. R.,Taylor, D. R.,Flannery, E. M.,Cowan, J. O.,Herbison, G. P.,Poulton, R. (2002). Long-term relation between breastfeeding and development of atopy and asthma in children and young adults: a longitudinal study Lancet, 360(9337), 901-7 | Intervention/exposure
2344 | Seethalakshmi,,Rao, K. M. (1985). No substitute to mother’s milk Nurs J India, 76(2), 48-9 | Study design
2345 | Seipel, M. M.,Shafer, K. (2013). The effect of prenatal and postnatal care on childhood obesity Soc Work, 58(3), 241-52 | Intervention/exposure
2346 | Selvakumar, B.,Vishnu Bhat, B. (2007). Infant feeding practice and its effect on the growth and development of babies Current Pediatric Research, 11(1-2), 13-16 | Country
2347 | Serino, R. J.,Gold, S. B. (1997). Infant and early childhood oral health care N Y State Dent J, 63(2), 34-5 | Study design
2348 | Serva, V.,Karim, H.,Ebrahim, G. J. (1986). Breast-feeding and the urban poor in developing countries J Trop Pediatr, 32(3), 127-9 | Outcome
2349 | Seske, L. M.,Merhar, S. L.,Haberman, B. E. (2015). Late-Onset Hypoglycemia in Term Newborns With Poor Breastfeeding Hosp Pediatr, 5(9), 501-4 | Study design
2350 | Seth A,Marwaha RK,Singla B,Aneja S,Mehrotra P,Sastry A,Khurana ML,Mani K,Sharma B,Tandon N (2009). Vitamin D nutritional status of exclusively breast fed infants and their mothers J Pediatr Endocrinol Metab, 22(#issue#), 241-6 | Country, Intervention/exposure
2351 | Sethi, D.,Cumberland, P.,Hudson, M. J.,Rodrigues, L. C.,Wheeler, J. G.,Roberts, J. A.,Tompkins, D. S.,Cowden, J. M.,Roderick, P. J. (2001). A study of infectious intestinal disease in England: risk factors associated with group A rotavirus in children Epidemiol Infect, 126(1), 63-70 | Intervention/exposure
2352 | Sethi, V.,Kashyap, S.,Seth, V. (2003). Effect of nutrition education of mothers on infant feeding practices Indian J Pediatr, 70(6), 463-6 | Country
2353 | Sezer, R. G.,Aydemir, G.,Akcan, A. B.,Bayoglu, D. S.,Guran, T.,Bozaykut, A. (2013). Effect of breastfeeding on serum zinc levels and growth in healthy infants Breastfeed Med, 8(#issue#), 159-63 | Study design
2354 | Shaaban, K. M.,Hamadnalla, I. (1993). The effect of duration of breast feeding on the occurrence of acute otitis media in children under three years East Afr Med J, 70(10), 632-4 | Country
2355 | Shalofsky, Teresa (2015). Telephone peer counselling of breastfeeding among WIC participants: a randomized controlled trial MIDIRS Midwifery Digest, 25(1), 97-98 2p | Publication status
2356 | Shamberger R (2012). Attention-deficit disorder associated with breast-feeding: a brief report J Am Coll Nutr, 31(#issue#), 239-42 | Study design
2357 | Shamir, R.,Nganga, A.,Berkowitz, D.,Diamond, E.,Lischinsky, S.,Lombardo, D.,Shehadeh, N. (2003). Serum levels of bile salt-stimulated lipase and breast feeding J Pediatr Endocrinol Metab, 16(9), 1289-94 | Size of study groups
2358 | Shand, N. (1981). The reciprocal impact of breast-feeding and culture form on maternal behaviour and infant development J Biosoc Sci, 13(1), 1-17 | Study design, Outcome
2359 | Shariff, A. H.,Sazlina, S. G.,Shamsul, A. S. (2007). Obesity among urban primary schoolchildren Journal of Health and Translational Medicine, 10(1), 17-20 | Study design
2360 | Sharifzadeh, G. R.,Namakin, K.,Mehrjoofard, H. (2008). An epidemiological study on infant mortatity and factors affecting it in rural areas of Birjand, Iran Iranian Journal of Pediatrics, 18(4), 335-342 | Outcome
2361 | Sharma, S.,Sood, M.,Sood, A. (2011). Environmental risk factors in relation to childhood asthma in rural area Current Pediatric Research, 15(1), 29-32 | Country
2362 | Shaternikov, V. A.,Fateeva, E. M.,Chernikov, M. N. (1982). Protein nutrition in early infancy and subsequent periods: its effect on further development Bibl Nutr Dieta, #volume#(31), 95-111 | Study design
2363 | Shearrer, G. E.,Whaley, S. E.,Miller, S. J.,House, B. T.,Held, T.,Davis, J. N. (2015). Association of gestational diabetes and breastfeeding on obesity prevalence in predominately Hispanic low-income youth Pediatr Obes, 10(3), 165-71 | Study design
2364 | Shehadeh, N.,Weitzer-Kish, H.,Shamir, R.,Shihab, S.,Weiss, R. (2008). Impact of early postnatal weight gain and feeding patterns on body mass index in adolescence J Pediatr Endocrinol Metab, 21(1), 9-15 | Intervention/exposure
2365 | Shelton, K. H.,Collishaw, S.,Rice, F. J.,Harold, G. T.,Thapar, A. (2011). Using a genetically informative design to examine the relationship between breastfeeding and childhood conduct problems Eur Child Adolesc Psychiatry, 20(11-12), 571-9 | Study design
2366 | Shepherd, J. (2002). Thrush and breastfeeding Pract Midwife, 5(11), 24-7 | Study design
2367 | Shepherd, R. W.,Oxborough, D. B.,Holt, T. L.,Thomas, B. J.,Thong, Y. H. (1988). Longitudinal study of the body composition of weight gain in exclusively breast-fed and intake-measured whey-based formula-fed infants to age 3 months J Pediatr Gastroenterol Nutr, 7(5), 732-9 | Outcome
2368 | Sherlock, R. L.,Synnes, A. R.,Koehoorn, M. (2008). Working mothers and early childhood outcomes: lessons from the Canadian National Longitudinal Study on Children and Youth Early Hum Dev, 84(4), 237-42 | Outcome
2369 | Shi, Y.,De Groh, M.,Morrison, H. (2013). Perinatal and early childhood factors for overweight and obesity in young Canadian children Can J Public Health, 104(1), e69-74 | Study design
2370 | Shields, B. M.,Knight, B.,Shakespeare, L.,Babrah, J.,Powell, R. J.,Clark, P. M.,Hattersley, A. T. (2006). Determinants of insulin concentrations in healthy 1-week-old babies in the community: applications of a bloodspot assay Early Hum Dev, 82(2), 143-8 | Study design, Outcome
2371 | Shields, L.,Mamun, A. A.,O’Callaghan, M.,Williams, G. M.,Najman, J. M. (2010). Breastfeeding and obesity at 21 years: a cohort study J Clin Nurs, 19(11-12), 1612-7 | Outcome
2372 | Shields, L.,O’Callaghan, M.,Williams, G. M.,Najman, J. M.,Bor, W. (2006). Breastfeeding and obesity at 14 years: a cohort study J Paediatr Child Health, 42(5), 289-96 | Outcome
2373 | Shohet, L.,Shahar, E.,Davidson, S. (1985). Breast feeding as prophylaxis for atopic eczema: a controlled study of 368 cases Acta Paediatr Hung, 26(1), 35-9 | Intervention/exposure
2374 | Shortridge, K. F.,Lawton, J. W.,Choi, E. K. (1990). Protective potential of colostrum and early milk against prospective influenza viruses J Trop Pediatr, 36(2), 94-5 | Study design, Outcome
2375 | Shu, X. O.,Clemens, J.,Zheng, W.,Ying, D. M.,Ji, B. T.,Jin, F. (1995). Infant breastfeeding and the risk of childhood lymphoma and leukaemia Int J Epidemiol, 24(1), 27-32 | Outcome
2376 | Shu, X. O.,Linet, M. S.,Steinbuch, M.,Wen, W. Q.,Buckley, J. D.,Neglia, J. P.,Potter, J. D.,Reaman, G. H.,Robison, L. L. (1999). Breast-feeding and risk of childhood acute leukemia J Natl Cancer Inst, 91(20), 1765-72 | Intervention/exposure
2377 | Shultis, W. A.,Leary, S. D.,Ness, A. R.,Scott, J.,Martin, R. M.,Whincup, P. H.,Smith, G. D. (2006). Haemoglobin A1c is not a surrogate for glucose and insulin measures for investigating the early life and childhood determinants of insulin resistance and Type 2 diabetes in healthy children. An analysis from the Avon Longitudinal Study of Parents and Children (ALSPAC) Diabet Med, 23(12), 1357-63 | Outcome
2378 | Sickles, V. S.,Tuley, R. J.,Bader, P.,Carnaggio, V. A.,Exon, W. J.,Hargett, I. R.,Keathley, S. E.,Wolf, R.,Cordano, A. (1984). Growth and tolerance studies of a new infant formula Clin Pediatr (Phila), 23(11), 617-22 | Intervention/exposure
2379 | Sidhu, L. S.,Grewal, R.,Bhatnagar, D. P. (1981). A study of physical growth in breast-fed and bottle-fed male infants Indian journal of pediatrics, 48(390), 75-79 | Country
2380 | Siemiatycki, J.,Colle, E.,Campbell, S.,Dewar, R. A.,Belmonte, M. M. (1989). Case-control study of IDDM Diabetes Care, 12(3), 209-16 | Outcome
2381 | Sievers, E.,Clausen, U.,Oldigs, H. D.,Schaub, J. (2002). Supplemental feeding in the first days of life - Effects on the recipient infant Annals of Nutrition and Metabolism, 46(2), 62-67 | Intervention/exposure
2382 | Sievers, E.,Oldigs, H. D.,Dorner, K.,Schaub, J. (1992). Longitudinal zinc balances in breast-fed and formula-fed infants Acta Paediatr, 81(1), 1-6 | Study design, Size of study groups
2383 | Sievers, E.,Schleyerbach, U.,Garbe-Schonberg, D.,Arpe, T.,Schaub, J. (2000). Zinc intakes and plasma concentrations in infancy Adv Exp Med Biol, 478(#issue#), 383-4 | Study design
2384 | Sigurs, N.,Bjarnason, R.,Sigurbergsson, F.,Kjellman, B.,Bjorksten, B. (1995). Asthma and immunoglobulin E antibodies after respiratory syncytial virus bronchiolitis: a prospective cohort study with matched controls Pediatrics, 95(4), 500-5 | Outcome
2385 | Siigur, U.,Ormisson, A.,Tamm, A. (1993). Faecal short-chain fatty acids in breast-fed and bottle-fed infants Acta Paediatrica, International Journal of Paediatrics, 82(6-7), 536-538 | Size of study groups, Outcome
2386 | Siimes, M. A.,Salmenpera, L.,Perheentupa, J. (1984). Exclusive breast-feeding for 9 months: Risk of iron deficiency Journal of Pediatrics, 104(2), 196-199 | Intervention/exposure
2387 | Silberman, S. L.,Trubman, A.,Duncan, W. K.,Meydrech, E. F. (1991). Prevalence of primary canine hypoplasia of the mandibular teeth Pediatr Dent, 13(6), 356-60 | Study design
2388 | Siltanen, M.,Kajosaari, M.,Poussa, T.,Saarinen, K. M.,Savilahti, E. (2003). A dual long-term effect of breastfeeding on atopy in relation to heredity in children at 4 years of age Allergy, 58(6), 524-30 | Intervention/exposure
2389 | Silva, A. A.,Mehta, Z.,O’Callaghan, F. J. (2006). Duration of breast feeding and cognitive function: Population based cohort study Eur J Epidemiol, 21(6), 435-41 | Outcome
2390 | Silver, D. H. (1982). Improvements in the dental health of 3-year-old Hertfordshire children after 8 years. The relationship to social class Br Dent J, 153(5), 179-83 | Study design
2391 | Silvers, K. M.,Frampton, C. M.,Wickens, K.,Epton, M. J.,Pattemore, P. K.,Ingham, T.,Fishwick, D.,Crane, J.,Town, G. I. (2009). Breastfeeding protects against adverse respiratory outcomes at 15 months of age Matern Child Nutr, 5(3), 243-50 | Outcome
2392 | Silvers, K. M.,Frampton, C. M.,Wickens, K.,Pattemore, P. K.,Ingham, T.,Fishwick, D.,Crane, J.,Town, G. I.,Epton, M. J. (2012). Breastfeeding protects against current asthma up to 6 years of age J Pediatr, 160(6), 991-6 e1 | Outcome
2393 | Simhon, A.,Mata, L. (1985). Fecal rotaviruses, adenoviruses, coronavirus-like particles, and small round viruses in a cohort of rural Costa Rican children Am J Trop Med Hyg, 34(5), 931-6 | Intervention/exposure
2394 | Simhon, A.,Mata, L.,Vives, M.,Rivera, L.,Vargas, S.,Ramirez, G.,Lizano, L.,Catarinella, G.,Azofeifa, J. (1985). Low endemicity and low pathogenicity of rotaviruses among rural children in Costa Rica J Infect Dis, 152(6), 1134-42 | Study design, Intervention/exposure
2395 | Simon, M. R.,Havstad, S. L.,Wegienka, G. R.,Ownby, D. R.,Johnson, C. C. (2008). Risk factors associated with transient wheezing in young children Allergy Asthma Proc, 29(2), 161-5 | Outcome
2396 | Sims, D. G.,Gardner, P. S.,Weightman, D.,Turner, M. W.,Soothill, J. F. (1981). Atopy does not predispose to RSV bronchiolitis or postbronchiolitic wheezing Br Med J (Clin Res Ed), 282(6282), 2086-8 | Size of study groups
2397 | Singhal, A. (2002). Early nutrition and later blood pressure: an experimental approach Journal of Nutritional & Environmental Medicine, 12(3), 251-252 2p | Study design
2398 | Singhal, A.,Kennedy, K.,Lanigan, J.,Clough, H.,Jenkins, W.,Elias-Jones, A.,Stephenson, T.,Dudek, P.,Lucas, A. (2010). Dietary nucleotides and early growth in formula-fed infants: a randomized controlled trial Pediatrics, 126(4), e946-53 | Outcome
2399 | Singhal, A.,Lucas, A. (2004). Early origins of cardiovascular disease: is there a unifying hypothesis? Lancet, 363(9421), 1642-5 | Study design
2400 | Singhal, A.,Morley, R.,Cole, T. J.,Kennedy, K.,Sonksen, P.,Isaacs, E.,Fewtrell, M.,Elias-Jones, A.,Stephenson, T.,Lucas, A. (2007). Infant nutrition and stereoacuity at age 4-6 y Am J Clin Nutr, 85(1), 152-9 | Outcome
2401 | Singhi, P.,Singhi, S.,Bhalla, A. K. (1985). Growth of term infants in early neonatal period Indian Pediatr, 22(7), 485-91 | Country
2402 | Singhi, S.,Singhi, P. (1987). Prevention of acute respiratory infections Indian J Pediatr, 54(2), 161-70 | Study design
2403 | Singleton, R.,Lescher, R.,Gessner, B. D.,Benson, M.,Bulkow, L.,Rosenfeld, J.,Thomas, T.,Holman, R. C.,Haberling, D.,Bruce, M.,Bartholomew, M.,Tiesinga, J. (2015). Rickets and Vitamin D deficiency in Alaska native children Journal of Pediatric Endocrinology and Metabolism, 28(7-8), 815-823 | Size of study groups, Intervention/exposure
2404 | Sinha, A.,Madden, J.,Ross-Degnan, D.,Soumerai, S.,Platt, R. (2003). Reduced risk of neonatal respiratory infections among breastfed girls but not boys Pediatrics, 112(4), e303 | Outcome
2405 | Sipetic, S.,Vlajinac, H.,Kocev, N.,Bjekic, M.,Sajic, S. (2005). Early infant diet and risk of type 1 diabetes mellitus in Belgrade children Nutrition, 21(4), 474-9 | Outcome
2406 | Sipila, M.,Karma, P.,Pukander, J.,Timonen, M.,Kataja, M. (1988). The Bayesian approach to the evaluation of risk factors in acute and recurrent acute otitis media Acta Otolaryngol, 106(1-2), 94-101 | Outcome
2407 | Siriaksorn, S.,Suchaitanawanit, S.,Trakultivakorn, M. (2011). Allergic rhinitis and immunoglobulin deficiency in preschool children with frequent upper respiratory illness Asian Pac J Allergy Immunol, 29(1), 73-7 | Study design
2408 | Sjolin, S.,Hofvander, Y.,Hillervik, C. (1979). A prospective study of individual courses of breast feeding Acta paediatrica Scandinavica, 68(#issue#), 521-9 | Outcome
2409 | Skilton, M. R.,Marks, G. B.,Ayer, J. G.,Garden, F. L.,Garnett, S. P.,Harmer, J. A.,Leeder, S. R.,Toelle, B. G.,Webb, K.,Baur, L. A.,Celermajer, D. S. (2013). Weight gain in infancy and vascular risk factors in later childhood Pediatrics, 131(6), e1821-8 | Outcome
2410 | Skledar, M. T.,Milosevic, M. (2015). Breastfeeding and time of complementary food introduction as predictors of obesity in children Cent Eur J Public Health, 23(1), 26-31 | Outcome
2411 | Skrodeniene, E.,Marciulionyte, D.,Padaiga, Z.,Jasinskiene, E.,Sadauskaite-Kuehne, V.,Ludvigsson, J. (2008). Environmental risk factors in prediction of childhood prediabetes Medicina (Kaunas), 44(1), 56-63 | Outcome
2412 | Skrodeniene, E.,Marčiulionyte, D.,Padaiga, Z.,Jašinskiene, E.,Sadauskaite-Kuehne, V.,Sanjeevi, C. B.,Vitkauskiene, A.,Ludvigsson, J. (2010). Associations between HLA class II haplotypes, environmental factors and type 1 diabetes mellitus in Lithuanian children with type 1 diabetes and controls Polish Annals of Medicine, 17(1), 7-15 | Outcome
2413 | Slabsinskiene E,Milciuviene S,Narbutaite J,Vasiliauskiene I,Andruskeviciene V,Bendoraitiene EA,Saldunaite K (2010). Severe early childhood caries and behavioral risk factors among 3-year-old children in Lithuania Medicina (Kaunas), 46(#issue#), 135-41 | Study design
2414 | Slae, M.,Persad, R.,Leung, A. J. T.,Gabr, R.,Brocks, D.,Huynh, H. Q. (2015). Role of Environmental Factors in the Development of Pediatric Eosinophilic Esophagitis Digestive Diseases and Sciences, 60(11), 3364-3372 | Study design, Outcome
2415 | Slavkin, H. C. (1999). Streptococcus mutans, early childhood caries and new opportunities J Am Dent Assoc, 130(12), 1787-92 | Study design
2416 | Slykerman, R. F.,Thompson, J. M.,Becroft, D. M.,Robinson, E.,Pryor, J. E.,Clark, P. M.,Wild, C. J.,Mitchell, E. A. (2005). Breastfeeding and intelligence of preschool children Acta Paediatr, 94(7), 832-7 | Outcome
2417 | Smith, D. P. (1985). Breastfeeding in the United States Soc Biol, 32(1-2), 53-60 | Study design, Outcome
2418 | Smith, R. M.,Smith, P. A.,McKinnon, M.,Gracey, M. (2000). Birthweights and growth of infants in five Aboriginal communities Aust N Z J Public Health, 24(2), 124-35 | Study design
2419 | Smithers, L. G.,Golley, R. K.,Brazionis, L.,Emmett, P.,Northstone, K.,Lynch, J. W. (2012). Dietary patterns of infants and toddlers are associated with nutrient intakes Nutrients, 4(8), 935-48 | Outcome
2420 | Smithers, L. G.,Golley, R. K.,Mittinty, M. N.,Brazionis, L.,Northstone, K.,Emmett, P.,Lynch, J. W. (2012). Dietary patterns at 6, 15 and 24 months of age are associated with IQ at 8 years of age Eur J Epidemiol, 27(7), 525-35 | Intervention/exposure
2421 | Smithers, L. G.,Golley, R. K.,Mittinty, M. N.,Brazionis, L.,Northstone, K.,Emmett, P.,Lynch, J. W. (2013). Do dietary trajectories between infancy and toddlerhood influence IQ in childhood and adolescence? Results from a prospective birth cohort study PLoS One, 8(3), e58904 | Intervention/exposure
2422 | Smulevich, V. B.,Solionova, L. G.,Belyakova, S. V. (1999). Parental occupation and other factors and cancer risk in children: I. Study methodology and non-occupational factors Int J Cancer, 83(6), 712-7 | Outcome
2423 | Smyth, P. P. (1999). Variation in iodine handling during normal pregnancy Thyroid, 9(7), 637-42 | Intervention/exposure, Redundant data with another study
2424 | Smyth, P. P.,Hetherton, A. M.,Smith, D. F.,Radcliff, M.,O’Herlihy, C. (1997). Maternal iodine status and thyroid volume during pregnancy: correlation with neonatal iodine intake J Clin Endocrinol Metab, 82(9), 2840-3 | Study design, Intervention/exposure
2425 | Smyth, P. P.,Smith, D. F.,Sheehan, S.,Higgins, M.,Burns, R.,O’Herlihy, C. (2007). Short-term changes in maternal and neonatal urinary iodine excretion Thyroid, 17(3), 219-22 | Size of study groups
2426 | Snijders, B. E.,Thijs, C.,Dagnelie, P. C.,Stelma, F. F.,Mommers, M.,Kummeling, I.,Penders, J.,van Ree, R.,van den Brandt, P. A. (2007). Breast-feeding duration and infant atopic manifestations, by maternal allergic status, in the first 2 years of life (KOALA study) J Pediatr, 151(4), 347-51, 351 e1-2 | Outcome
2427 | Snijders, B. E.,Thijs, C.,Kummeling, I.,Penders, J.,van den Brandt, P. A. (2007). Breastfeeding and infant eczema in the first year of life in the KOALA birth cohort study: a risk period-specific analysis Pediatrics, 119(1), e137-41 | Outcome
2428 | Socha, P.,Grote, V.,Gruszfeld, D.,Janas, R.,Demmelmair, H.,Closa-Monasterolo, R.,Subias, J. E.,Scaglioni, S.,Verduci, E.,Dain, E.,Langhendries, J. P.,Perrin, E.,Koletzko, B. (2011). Milk protein intake, the metabolic-endocrine response, and growth in infancy: data from a randomized clinical trial Am J Clin Nutr, 94(6 Suppl), 1776S-1784S | Outcome
2429 | Socha, P.,Janas, R.,Dobrzanska, A.,Koletzko, B.,Broekaert, I.,Brasseur, D.,Sengier, A.,Giovannini, M.,Agostoni, C.,Monasterolo, R. C.,Mendezs, G. (2005). Insulin like growth factor regulation of body mass in breastfed and milk formula fed infants. Data from the E.U. Childhood Obesity Programme Adv Exp Med Biol, 569(#issue#), 159-63 | Study design
2430 | Soltesz, G.,Jeges, S.,Dahlquist, G. (1994). Non-genetic risk determinants for type 1 (insulin-dependent) diabetes mellitus in childhood. Hungarian Childhood Diabetes Epidemiology Study Group Acta Paediatr, 83(7), 730-5 | Outcome
2431 | Somech, R.,Tal, G.,Gilad, E.,Mandelberg, A.,Tal, A.,Dalal, I. (2006). Epidemiologic, socioeconomic, and clinical factors associated with severity of respiratory syncytial virus infection in previously healthy infants Clin Pediatr (Phila), 45(7), 621-7 | Participant health
2432 | Sommerfelt, K.,Ellertsen, B.,Markestad, T. (1996). Low birthweight and neuromotor development: a population based, controlled study Acta Paediatr, 85(5), 604-10 | Participant health, Intervention/exposure
2433 | Sommerfield, T.,Chalmers, J.,Youngson, G.,Heeley, C.,Fleming, M.,Thomson, G. (2008). The changing epidemiology of infantile hypertrophic pyloric stenosis in Scotland Arch Dis Child, 93(12), 1007-11 | Study design, Intervention/exposure, Participant health
2434 | Song, N.,Shamssain, M.,Zhang, J.,Wu, J.,Fu, C.,Hao, S.,Guan, J.,Yan, X. (2014). Prevalence, severity and risk factors of asthma, rhinitis and eczema in a large group of Chinese schoolchildren J Asthma, 51(3), 232-42 | Study design
2435 | Sonnenschein-van der Voort, A. M.,Jaddoe, V. W.,van der Valk, R. J.,Willemsen, S. P.,Hofman, A.,Moll, H. A.,de Jongste, J. C.,Duijts, L. (2012). Duration and exclusiveness of breastfeeding and childhood asthma-related symptoms Eur Respir J, 39(1), 81-9 | Outcome
2436 | Soto-Ramirez, N.,Karmaus, W.,Zhang, H.,Davis, S.,Agarwal, S.,Albergottie, A. (2013). Modes of infant feeding and the occurrence of coughing/wheezing in the first year of life J Hum Lact, 29(1), 71-80 | Outcome
2437 | Soylu, H.,Özgen, Ü,Babalioǧlu, M.,Aras, Ş,Sazak, S. (2001). Iron deficiency and iron deficiency anemia in infants and young children at different socioeconomic groups in Istanbul Turkish Journal of Haematology, 18(1), 19-25 | Study design, Size of study groups
2438 | Specker, B. L.,Beck, A.,Kalkwarf, H.,Ho, M. (1997). Randomized trial of varying mineral intake on total body bone mineral accretion during the first year of life Pediatrics, 99(6), E12 | Intervention/exposure
2439 | Specker, B. L.,Black, A.,Allen, L.,Morrow, F. (1990). Vitamin B-12: low milk concentrations are related to low serum concentrations in vegetarian women and to methylmalonic aciduria in their infants Am J Clin Nutr, 52(6), 1073-6 | Study design, Size of study groups
2440 | Specker, B. L.,Brazerol, W.,Ho, M. L.,Norman, E. J. (1990). Urinary methylmalonic acid excretion in infants fed formula or human milk Am J Clin Nutr, 51(2), 209-11 | Study design, Intervention/exposure
2441 | Specker, B. L.,Miller, D.,Norman, E. J.,Greene, H.,Hayes, K. C. (1988). Increased urinary methylmalonic acid excretion in breast-fed infants of vegetarian mothers and identification of an acceptable dietary source of vitamin B-12 Am J Clin Nutr, 47(1), 89-92 | Study design, Size of study groups
2442 | Spyrides, M. H.,Struchiner, C. J.,Barbosa, M. T.,Kac, G. (2008). Effect of predominant breastfeeding duration on infant growth: a prospective study using nonlinear mixed effect models J Pediatr (Rio J), 84(3), 237-43 | Language
2443 | Srivastava, S. P.,Sharma, V. K.,Jha, S. P. (1994). Mortality patterns in breast versus artificially fed term babies in early infancy: a longitudinal study Indian Pediatr, 31(11), 1393-6 | Country
2444 | Stadler, D. D.,Musser, E. D.,Holton, K. F.,Shannon, J.,Nigg, J. T. (2015). Recalled Initiation and Duration of Maternal Breastfeeding Among Children with and Without ADHD in a Well Characterized Case-Control Sample J Abnorm Child Psychol, #volume#(#issue#), #Pages# | Study design
2445 | Stahl, M. D.,Guida, D. A. (1984). Slow weight gain in the breast-fed infant: management options Pediatr Nurs, 10(2), 117-20, 164 | Study design
2446 | Stahlberg, M. R. (1985). Breast feeding, cow milk feeding, and allergy Allergy, 40(8), 612-5 | Outcome
2447 | Stahlberg, M. R.,Ruuskanen, O.,Virolainen, E. (1986). Risk factors for recurrent otitis media Pediatr Infect Dis, 5(1), 30-2 | Outcome
2448 | Standl, M.,Sausenthaler, S.,Lattka, E.,Koletzko, S.,Bauer, C. P.,Wichmann, H. E.,von Berg, A.,Berdel, D.,Kramer, U.,Schaaf, B.,Lehmann, I.,Herbarth, O.,Klopp, N.,Koletzko, B.,Heinrich, J. (2012). FADS gene cluster modulates the effect of breastfeeding on asthma. Results from the GINIplus and LISAplus studies Allergy, 67(1), 83-90 | Intervention/exposure
2449 | Stanfield JP (1982). The influence of malnutrition on development Practitioner, 226(#issue#), 1929-40 | Study design
2450 | Stanley, E. O.,Lundeen, D. J. (1980). Tongue thrust in breast fed and bottle-fed school children: a cross-cultural investigation Int J Oral Myol, 6(1), 6-17 | Intervention/exposure, Outcome
2451 | Stanner, S. (2001). Is breast best for the heart? Nutrition Bulletin, 26(3), 199-200 | Study design
2452 | Steady, F. C. (1981). Infant feeding in developing countries: combating the multinationals imperative J Trop Pediatr, 27(4), 215-20 | Study design
2453 | Stecksen-Blicks, C.,Granstrom, E.,Silfverdal, S. A.,West, C. E. (2015). Prevalence of oral Candida in the first year of life Mycoses, 58(9), 550-6 | Size of study groups
2454 | Steer, C. D.,Davey Smith, G.,Emmett, P. M.,Hibbeln, J. R.,Golding, J. (2010). FADS2 polymorphisms modify the effect of breastfeeding on child IQ PLoS One, 5(7), e11570 | Outcome
2455 | Steichen, J. J.,Tsang, R. C. (1987). Bone mineralization and growth in term infants fed soy-based or cow milk-based formula J Pediatr, 110(5), 687-92 | Size of study groups, Intervention/exposure
2456 | Stein, A. D.,Melgar, P.,Hoddinott, J.,Martorell, R. (2008). Cohort profile: The institute of nutrition of central America and Panama (INCAP) nutrition trial cohort study International Journal of Epidemiology, 37(4), 716-720 | Study design
2457 | Stelmach, I.,Bobrowska-Korzeniowska, M.,Smejda, K.,Majak, P.,Jerzynska, J.,Stelmach, W.,Polanska, K.,Sobala, W.,Krysicka, J.,Hanke, W. (2014). Risk factors for the development of atopic dermatitis and early wheeze Allergy Asthma Proc, 35(5), 382-9 | Study design
2458 | Stene, L. C.,Joner, G. (2004). Atopic disorders and risk of childhood-onset type 1 diabetes in individuals Clin Exp Allergy, 34(2), 201-6 | Study design, Intervention/exposure
2459 | Stenstrom, C.,Ingvarsson, L. (1997). Otitis-prone children and controls: a study of possible predisposing factors. 1. Heredity, family background and perinatal period Acta Otolaryngol, 117(1), 87-93 | Outcome
2460 | Stepans, M. F. (1998). Birthing briefs Journal of Perinatal Education, 7(1), 39-40 2p | Study design
2461 | Stevens, F. M.,Egan-Mitchell, B.,Cryan, E.,McCarthy, C. F.,McNicholl, B. (1987). Decreasing incidence of coeliac disease Arch Dis Child, 62(5), 465-8 | Study design, Size of study groups
2462 | Stevens, T. (1996). Infant nutrition perspectives Midwives (1995), 109(1300), 120 | Study design
2463 | Stewart, A. J.,Williams, S. M.,Mitchell, E. A.,Taylor, B. J.,Ford, R. P.,Allen, E. M. (1995). Antenatal and intrapartum factors associated with sudden infant death syndrome in the New Zealand Cot Death Study J Paediatr Child Health, 31(5), 473-8 | Intervention/exposure
2464 | Stoeckel, J. (1992). The intervention research approach to child survival Asia Pac J Public Health, 6(1), 40-5 | Study design
2465 | Stoll, B. J.,Glass, R. I.,Banu, H.,Huq, M. I.,Khan, M. U.,Ahmed, M. (1983). Value of stool examination in patients with diarrhoea Br Med J (Clin Res Ed), 286(6383), 2037-40 | Country
2466 | Stordal, K.,White, R. A.,Eggesbo, M. (2013). Early feeding and risk of celiac disease in a prospective birth cohort Pediatrics, 132(5), e1202-9 | Outcome
2467 | Strabelli, T. M. B.,Botura, C. A.,Maciel, M. A.,Mazzutti, C.,Bridi, A.,Freitas, L. P. (2013). Socioeconomic profile of children hospitalized by community acquired pneumonia Acta Scientiarum - Health Sciences, 35(2), 175-179 | Study design, Participant health
2468 | Strachan, D. P.,Harkins, L. S.,Johnston, I. D.,Anderson, H. R. (1997). Childhood antecedents of allergic sensitization in young British adults J Allergy Clin Immunol, 99(1 Pt 1), 6-12 | Intervention/exposure
2469 | Strachan, D. P.,Taylor, E. M.,Carpenter, R. G. (1996). Family structure, neonatal infection, and hay fever in adolescence Arch Dis Child, 74(5), 422-6 | Intervention/exposure
2470 | Strand, T. A.,Sharma, P. R.,Gjessing, H. K.,Ulak, M.,Chandyo, R. K.,Adhikari, R. K.,Sommerfelt, H. (2012). Risk factors for extended duration of acute diarrhea in young children PLoS One, 7(5), e36436 | Country
2471 | Strand, T. A.,Taneja, S.,Bhandari, N.,Refsum, H.,Ueland, P. M.,Gjessing, H. K.,Bahl, R.,Schneede, J.,Bhan, M. K.,Sommerfelt, H. (2007). Folate, but not vitamin B-12 status, predicts respiratory morbidity in north Indian children Am J Clin Nutr, 86(1), 139-44 | Country
2472 | Strandvik B,Chen Y,Dangardt F,Eriksson S,Friberg P,Garemo M,Pickova J (2011). From the Swedish to the Mediterranean diet and the omega-6/omega-3 balance World Rev Nutr Diet, 102(#issue#), 73-80 | Study design
2473 | Strassburger, S. Z.,Vitolo, M. R.,Bortolini, G. A.,Pitrez, P. M.,Jones, M. H.,Stein, R. T. (2010). Nutritional errors in the first months of life and their association with asthma and atopy in preschool children J Pediatr (Rio J), 86(5), 391-9 | Outcome
2474 | Strbak, V.,Hromadova, M.,Kostalova, L.,Kapellerova, A. (1993). Search for optimal age for weaning. Ten-year prospective study Endocr Regul, 27(4), 215-21 | Size of study groups
2475 | Strbak, V.,Skultetyova, M.,Hromadova, M.,Randuskova, A.,Macho, L. (1991). Late effects of breast-feeding and early weaning: seven-year prospective study in children Endocr Regul, 25(1-2), 53-7 | Outcome
2476 | Stremler, R.,Hodnett, E.,Kenton, L.,Lee, K.,Weiss, S.,Weston, J.,Willan, A. (2013). Effect of behavioural-educational intervention on sleep for primiparous women and their infants in early postpartum: multisite randomised controlled trial BMJ, 346(#issue#), f1164 | Intervention/exposure
2477 | Strimas, J. H.,Chi, D. S. (1988). Significance of IgE level in amniotic fluid and cord blood for the prediction of allergy Ann Allergy, 61(2), 133-6 | Size of study groups, Intervention/exposure
2478 | Strina, A.,Rodrigues, L. C.,Cairncross, S.,Ferrer, S. R.,Fialho, A. M.,Leite, J. P.,Ribeiro, H. C., Jr.,Barreto, M. L. (2012). Factors associated with rotavirus diarrhoea in children living in a socially diverse urban centre in Brazil Trans R Soc Trop Med Hyg, 106(7), 445-51 | Study design, Intervention/exposure
2479 | Strobl, W.,Widhalm, K. (1985). The natural history of serum lipids and lipoproteins during childhood Prog Clin Biol Res, 188(#issue#), 101-21 | Study design
2480 | Su, D.,Zhao, Y.,Binns, C.,Scott, J.,Oddy, W. (2007). Breast-feeding mothers can exercise: results of a cohort study Public Health Nutr, 10(10), 1089-93 | Intervention/exposure
2481 | Suaini, N. H.,Koplin, J. J.,Ellis, J. A.,Peters, R. L.,Ponsonby, A. L.,Dharmage, S. C.,Matheson, M. C.,Wake, M.,Panjari, M.,Tan, H. T.,Martin, P. E.,Pezic, A.,Lowe, A. J.,Martino, D.,Gurrin, L. C.,Vuillermin, P. J.,Tang, M. L.,Allen, K. J. (2014). Environmental and genetic determinants of vitamin D insufficiency in 12-month-old infants J Steroid Biochem Mol Biol, 144 Pt B(#issue#), 445-54 | Intervention/exposure
2482 | Subbarao, P.,Anand, S. S.,Becker, A. B.,Befus, A. D.,Brauer, M.,Brook, J. R.,Denburg, J. A.,Hayglass, K. T.,Kobor, M. S.,Kollmann, T. R.,Kozyrskyj, A. L.,Lou, W. Y. W.,Mandhane, P. J.,Miller, G. E.,Moraes, T. J.,Pare, P. D.,Scott, J. A.,Takaro, T. K.,Turvey, S. E.,Duncan, J. M.,Lefebvre, D. L.,Sears, M. R. (2015). The Canadian Healthy Infant Longitudinal Development (CHILD) study: Examining developmental origins of allergy and asthma Thorax, 70(10), 998-1000 | Study design
2483 | Suganuma, E. K.,Alexander, G. R.,Baruffi, G.,Gilden, S. R. (1988). Infant feeding practices in Hawaii Hawaii Med J, 47(3), 112, 117-9 | Study design
2484 | Sun, G.,Jia, G.,Peng, H.,Dickerman, B.,Compher, C.,Liu, J. (2015). Trends of childhood obesity in China and associated factors Clin Nurs Res, 24(2), 156-71 | Study design, Size of study groups
2485 | Sun, J.,Huo, J.,Zhao, L.,Fu, P.,Wang, J.,Huang, J.,Wang, L.,Song, P.,Fang, Z.,Chang, S.,Yin, S.,Zhang, J.,Ma, G. (2013). The nutritional status of young children and feeding practices two years after the Wenchuan Earthquake in the worst-affected areas in China Asia Pac J Clin Nutr, 22(1), 100-8 | Study design, Intervention/exposure
2486 | Sunoto, (1982). Diarrhoeal problems in Southeast Asia Southeast Asian J Trop Med Public Health, 13(3), 306-18 | Study design
2487 | Sunyer, J.,Torrent, M.,Garcia-Esteban, R.,Ribas-Fito, N.,Carrizo, D.,Romieu, I.,Anto, J. M.,Grimalt, J. O. (2006). Early exposure to dichlorodiphenyldichloroethylene, breastfeeding and asthma at age six Clin Exp Allergy, 36(10), 1236-41 | Outcome
2488 | Suoglu, O. D.,Gokce, S.,Saglam, A. T.,Sokucu, S.,Saner, G. (2007). Association of Helicobacter pylori infection with gastroduodenal disease, epidemiologic factors and iron-deficiency anemia in Turkish children undergoing endoscopy, and impact on growth Pediatr Int, 49(6), 858-63 | Intervention/exposure
2489 | Surdu, S.,Montoya, L. D.,Tarbell, A.,Carpenter, D. O. (2006). Childhood asthma and indoor allergens in Native Americans in New York Environ Health, 5(#issue#), 22 | Size of study groups
2490 | Sussmann, J. E.,McIntosh, A. M.,Lawrie, S. M.,Johnstone, E. C. (2009). Obstetric complications and mild to moderate intellectual disability Br J Psychiatry, 194(3), 224-8 | Size of study groups, Intervention/exposure
2491 | Sutmoller, F.,Maia, P. R. (1995). Acute respiratory infections in children living in two low income communities of Rio de Janeiro, Brazil Mem Inst Oswaldo Cruz, 90(6), 665-74 | Outcome
2492 | Syafruddin, M.,Djauhariah, A. M.,Dasril, D. (1988). A study comparing rooming-in with separate nursing Paediatr Indones, 28(5-6), 116-23 | Country
2493 | Tada, A.,Ando, Y.,Hanada, N. (1999). Caries risk factors among three-year old children in Chiba, Japan Asia Pac J Public Health, 11(2), 109-12 | Outcome
2494 | Tai, T. Y.,Wang, C. Y.,Lin, L. L.,Lee, L. T.,Tsai, S. T.,Chen, C. J. (1998). A case-control study on risk factors for Type 1 diabetes in Taipei City Diabetes Res Clin Pract, 42(3), 197-203 | Outcome
2495 | Tainio, V. M. (1985). Lymphocyte subsets in infants: relationships to feeding, atopy, atopic heredity and infections Int Arch Allergy Appl Immunol, 78(3), 305-10 | Outcome
2496 | Tainio, V. M.,Savilahti, E.,Salmenpera, L.,Arjomaa, P.,Siimes, M. A.,Perheentupa, J. (1988). Risk factors for infantile recurrent otitis media: atopy but not type of feeding Pediatr Res, 23(5), 509-12 | Outcome
2497 | Taittonen, L.,Nuutinen, M.,Turtinen, J.,Uhari, M. (1996). Prenatal and postnatal factors in predicting later blood pressure among children: cardiovascular risk in young Finns Pediatr Res, 40(4), 627-32 | Outcome
2498 | Taitz, L. S.,Lukmanji, Z. (1981). Alterations in feeding patterns and rates of weight gain in South Yorkshire infants, 1971-1977 Hum Biol, 53(3), 313-20 | Study design
2499 | Takala, A. K.,Eskola, J.,Palmgren, J.,Ronnberg, P. R.,Kela, E.,Rekola, P.,Makela, P. H. (1989). Risk factors of invasive Haemophilus influenzae type b disease among children in Finland J Pediatr, 115(5 Pt 1), 694-701 | Outcome
2500 | Takemura, Y.,Sakurai, Y.,Honjo, S.,Kusakari, A.,Hara, T.,Gibo, M.,Tokimatsu, A.,Kugai, N. (2001). Relation between breastfeeding and the prevalence of asthma : the Tokorozawa Childhood Asthma and Pollinosis Study Am J Epidemiol, 154(2), 115-9 | Study design
2501 | Taki, M.,Mizuno, K.,Murase, M.,Nishida, Y.,Itabashi, K.,Mukai, Y. (2010). Maturational changes in the feeding behaviour of infants - a comparison between breast-feeding and bottle-feeding Acta Paediatr, 99(1), 61-7 | Size of study groups
2502 | Talayero, J. M. P.,Lizán-García, M.,Puime Á, O.,Muncharaz, M. J. B.,Soto, B. B.,Sánchez-Palomares, M.,Serrano, L. S.,Rivera, L. L. (2006). Full breastfeeding and hospitalization as a result of infections in the first year of life Pediatrics, 118(1), e92-e99 | Outcome
2503 | Tanaka, H.,Ishii, H.,Yamada, T.,Akazawa, K.,Nagata, S.,Yamashiro, Y. (2013). Growth of Japanese breastfed infants compared to national references and World Health Organization growth standards Acta Paediatr, 102(7), 739-43 | Intervention/exposure
2504 | Tanaka, K.,Miyake, Y.,Sasaki, S. (2010). Association between breastfeeding and allergic disorders in Japanese children Int J Tuberc Lung Dis, 14(4), 513-8 | Study design
2505 | Tanaka, K.,Miyake, Y.,Sasaki, S.,Hirota, Y. (2013). Infant feeding practices and risk of dental caries in Japan: the Osaka Maternal And Child Health Study Pediatr Dent, 35(3), 267-71 | Outcome
2506 | Tanaka, T.,Kato, N. (2001). Evaluation of child care practice factors that affect the occurrence of sudden infant death syndrome: Interview conducted by public health nurses Environmental Health and Preventive Medicine, 6(2), 117-120 | Outcome
2507 | Taneja, S.,Bhandari, N.,Bahl, R.,Bhan, M. K. (2005). Impact of zinc supplementation on mental and psychomotor scores of children aged 12 to 18 months: a randomized, double-blind trial J Pediatr, 146(4), 506-11 | Country
2508 | Taneja, S.,Bhandari, N.,Strand, T. A.,Sommerfelt, H.,Refsum, H.,Ueland, P. M.,Schneede, J.,Bahl, R.,Bhan, M. K. (2007). Cobalamin and folate status in infants and young children in a low-to-middle income community in India Am J Clin Nutr, 86(5), 1302-9 | Country
2509 | Tanoue, Y.,Oda, S. (1989). Weaning time of children with infantile autism J Autism Dev Disord, 19(3), 425-34 | Study design, Intervention/exposure
2510 | Tantracheewathorn, S. (2005). Growth of breast-fed and formula-fed infants compared with national growth references of Thai children J Med Assoc Thai, 88(2), 168-75 | Intervention/exposure
2511 | Tantracheewathorn, S.,Lohajaroensub, S. (2005). Incidence and risk factors of iron deficiency anemia in term infants J Med Assoc Thai, 88(1), 45-51 | Intervention/exposure
2512 | Tanzer, F.,Gumuser, C. (1989). A study of the growth of 200 newborn babies for a period of 6 months according to the type of nutrition Ann Trop Paediatr, 9(1), 54-8 | Size of study groups
2513 | Targino, A. G.,Rosenblatt, A.,Oliveira, A. F.,Chaves, A. M.,Santos, V. E. (2011). The relationship of enamel defects and caries: a cohort study Oral Dis, 17(4), 420-6 | Intervention/exposure
2514 | Tariq, S.,Memon, I. A. (1999). Acute otitis media in children Journal of the College of Physicians and Surgeons Pakistan, 9(12), 507-510 | Country
2515 | Tarrant, M.,Fong, D. Y.,Heys, M.,Lee, I. L.,Sham, A.,Hui Choi, E. W. (2014). Professional breastfeeding support to increase the exclusivity and duration of breastfeeding: a randomised controlled trial Hong Kong Med J, 20 Suppl 7(#issue#), 34-5 | Study design, Outcome
2516 | Tarrant, M.,Kwok, M. K.,Lam, T. H.,Leung, G. M.,Schooling, C. M. (2010). Breast-feeding and childhood hospitalizations for infections Epidemiology, 21(6), 847-54 | Outcome
2517 | Tarrant, M.,Schooling, C. M.,Leung, S. L.,Mak, K. H.,Ho, L. M.,Leung, G. M. (2014). Impact of breastfeeding on infectious disease hospitalisation: the children of 1997 cohort Hong Kong Med J, 20 Suppl 4(#issue#), 5-6 | Study design
2518 | Tarrant, R. C.,Sheridan-Pereira, M.,Younger, K. M.,Kearney, J. M. (2012). The positive role of breastfeeding on infant health during the first 6 weeks: findings from a prospective observational study based on maternal reports Ir Med J, 105(3), 75-8 | Study design
2519 | Taveras, E. M.,Gillman, M. W.,Kleinman, K. P.,Rich-Edwards, J. W.,Rifas-Shiman, S. L. (2013). Reducing racial/ethnic disparities in childhood obesity: the role of early life risk factors JAMA Pediatr, 167(8), 731-8 | Intervention/exposure
2520 | Taveras, E. M.,Gillman, M. W.,Kleinman, K.,Rich-Edwards, J. W.,Rifas-Shiman, S. L. (2010). Racial/ethnic differences in early-life risk factors for childhood obesity Pediatrics, 125(4), 686-95 | Outcome
2521 | Taveras, E. M.,Rifas-Shiman, S. L.,Scanlon, K. S.,Grummer-Strawn, L. M.,Sherry, B.,Gillman, M. W. (2006). To what extent is the protective effect of breastfeeding on future overweight explained by decreased maternal feeding restriction? Pediatrics, 118(6), 2341-8 | Outcome
2522 | Tawia S (2013). Childhood obesity and being breastfed Breastfeed Rev, 21(#issue#), 42-8 | Study design
2523 | Taylor, B. (1984). Infant feeding and allergy: fact and fiction Midwife Health Visit Community Nurse, 20(10), 354-60 | Study design
2524 | Taylor, B.,Wadsworth, J. (1984). Breast feeding and child development at five years Dev Med Child Neurol, 26(1), 73-80 | Study design
2525 | Taylor, B.,Wadsworth, J.,Golding, J.,Butler, N. (1982). Breast-feeding, bronchitis, and admissions for lower-respiratory illness and gastroenteritis during the first five years Lancet, 1(8283), 1227-9 | Study design, Intervention/exposure
2526 | Taylor, B.,Wadsworth, J.,Golding, J.,Butler, N. (1983). Breast feeding, eczema, asthma, and hayfever J Epidemiol Community Health, 37(2), 95-9 | Intervention/exposure
2527 | Taylor, R. (2014). Providing additional guidance and support to parents about sleep, diet and physical activity from birth to 2 years of age: The Prevention of Overweight in Infancy study Obesity research & clinical practice, 8(#issue#), 102-3 | Publication status
2528 | Taylor-Robinson, D. C.,Williams, H.,Pearce, A.,Law, C.,Hope, S. (2015). Do early life exposures explain why more advantaged children get eczema? Findings from the UK Millennium Cohort Study Br J Dermatol, #volume#(#issue#), #Pages# | Study design
2529 | Tee, J. H. (1987). Some characteristics of 5-year-old children with a dmf of six or more in Gloucestershire, England Community Dent Health, 4(2), 121-8 | Study design
2530 | Teele, D. W.,Klein, J. O.,Rosner, B. (1989). Epidemiology of otitis media during the first seven years of life in children in greater Boston: a prospective, cohort study J Infect Dis, 160(1), 83-94 | Outcome
2531 | Teixeira Mde, L.,Lira, P. I.,Coutinho, S. B.,Eickmann, S. H.,Lima, M. C. (2010). Influence of breastfeeding type and maternal anemia on hemoglobin concentration in 6-month-old infants J Pediatr (Rio J), 86(1), 65-72 | Study design
2532 | Teixeira, Ana Karine Macedo,Menezes, LÃ©a Maria Bezerra de,Dias, Aldo Angelim,Alencar, Carlos Henrique Morais de,Almeida, Maria Eneide LeitÃ£o de (2010). Analysis of protection or risk factors for dental fluorosis in 6 to 8 year-old children in Fortaleza, Brazil Revista Panamericana de Salud Publica, 28(6), 421-428 8p | Language
2533 | Teka, T.,Faruque, A. S.,Fuchs, G. J. (1996). Risk factors for deaths in under-age-five children attending a diarrhoea treatment centre Acta Paediatr, 85(9), 1070-5 | Country
2534 | Telahun, M.,Abdulkadir, J.,Kebede, E. (1994). The relation of early nutrition, infections and socio-economic factors to the development of childhood diabetes Ethiop Med J, 32(4), 239-44 | Country
2535 | Temboury, M. C.,Otero, A.,Polanco, I.,Arribas, E. (1994). Influence of breast-feeding on the infant’s intellectual development J Pediatr Gastroenterol Nutr, 18(1), 32-6 | Intervention/exposure
2536 | Tenebaum, D.,Gambert, P.,Meunier, S.,d’Athis, P.,Nivelon, J. L.,Lallemand, C. (1988). Serum lipoproteins in venous blood serum from birth to the end of the first week: feeding influences Biol Neonate, 53(3), 126-31 | Size of study groups
2537 | Thacher, T. D.,Fischer, P. R.,Tebben, P. J.,Singh, R. J.,Cha, S. S.,Maxson, J. A.,Yawn, B. P. (2013). Increasing incidence of nutritional rickets: a population-based study in Olmsted County, Minnesota Mayo Clin Proc, 88(2), 176-83 | Study design, Size of study groups
2538 | Thakur, R.,Singh, M. G.,Chaudhary, S.,Manuja, N. (2012). Effect of mode of delivery and feeding practices on acquisition of oral Streptococcus mutans in infants Int J Paediatr Dent, 22(3), 197-202 | Country, Size of study group
2539 | Thapa, S.,Short, R. V.,Potts, M. (1988). Breast feeding, birth spacing and their effects on child survival Nature, 335(6192), 679-82 | Study design
2540 | Thaver, I. H. (1990). “Risk approach” for reducing malnutrition in children from a privileged community J Pak Med Assoc, 40(3), 59-61 | Country
2541 | Thiering, E.,Bruske, I.,Kratzsch, J.,Thiery, J.,Sausenthaler, S.,Meisinger, C.,Koletzko, S.,Bauer, C. P.,Schaaf, B.,von Berg, A.,Berdel, D.,Lehmann, I.,Herbarth, O.,Kramer, U.,Wichmann, H. E.,Heinrich, J. (2011). Prenatal and postnatal tobacco smoke exposure and development of insulin resistance in 10 year old children Int J Hyg Environ Health, 214(5), 361-8 | Intervention/exposure
2542 | Thies, P. A.,Jeris, L. S. (1981). Infant feeding practices and dental health. Part 2: breastfeeding and dental caries Bull Mich Dent Hyg Assoc, 11(1), 6-7, 20 | Study design
2543 | Thitasomakul, S.,Piwat, S.,Thearmontree, A.,Chankanka, O.,Pithpornchaiyakul, W.,Madyusoh, S. (2009). Risks for early childhood caries analyzed by negative binomial models J Dent Res, 88(2), 137-41 | Study design, Size of study groups
2544 | Thomas, G. P.,Soni, N. N. (1987). Clinical manifestations and management of nursing bottle syndrome J Md State Dent Assoc, 30(2), 62-4 | Study design
2545 | Thomaz, E. B.,Cangussu, M. C.,Assis, A. M. (2012). Maternal breastfeeding, parafunctional oral habits and malocclusion in adolescents: a multivariate analysis Int J Pediatr Otorhinolaryngol, 76(4), 500-6 | Study design
2546 | Thompson, A. L.,Adair, L. S.,Bentley, M. E. (2013). Pressuring and restrictive feeding styles influence infant feeding and size among a low-income African-American sample Obesity (Silver Spring), 21(3), 562-71 | Intervention/exposure
2547 | Thompson, A. L.,Lampl, M. (2013). Prenatal and postnatal energetic conditions and sex steroids levels across the first year of life Am J Hum Biol, 25(5), 643-54 | Outcome, Size of study groups
2548 | Thompson, M. (1987). Think zinc Neonatal Netw, 6(1), 44-5 | Study design
2549 | Thompson, N. P.,Montgomery, S. M.,Wadsworth, M. E.,Pounder, R. E.,Wakefield, A. J. (2000). Early determinants of inflammatory bowel disease: use of two national longitudinal birth cohorts Eur J Gastroenterol Hepatol, 12(1), 25-30 | Size of study groups
2550 | Thomsen, S. F.,Ulrik, C. S.,Porsbjerg, C.,Backer, V. (2006). Early life exposures and risk of atopy among Danish children Allergy Asthma Proc, 27(2), 110-4 | Study design, Outcome
2551 | Thomson, J. L.,Tussing-Humphreys, L. M.,Goodman, M. H. (2014). Delta Healthy Sprouts: a randomized comparative effectiveness trial to promote maternal weight control and reduce childhood obesity in the Mississippi Delta Contemp Clin Trials, 38(1), 82-91 | Study design, Outcome
2552 | Thomson, K.,Morley, R.,Grover, S. R.,Zacharin, M. R. (2004). Postnatal evaluation of vitamin D and bone health in women who were vitamin D-deficient in pregnancy, and in their infants Med J Aust, 181(9), 486-8 | Size of study groups
2553 | Thomson, M. (1994). Otitis media. How are First Nations children affected? Can Fam Physician, 40(#issue#), 1943-50 | Study design, Intervention/exposure
2554 | Thorisdottir, A. V.,Ramel, A.,Palsson, G. I.,Tomassson, H.,Thorsdottir, I. (2013). Iron status of one-year-olds and association with breast milk, cow’s milk or formula in late infancy Eur J Nutr, 52(6), 1661-8 | Intervention/exposure
2555 | Thorpe, K.,Rutter, M.,Greenwood, R. (2003). Twins as a natural experiment to study the causes of mild language delay: II: Family interaction risk factors J Child Psychol Psychiatry, 44(3), 342-55 | Outcome
2556 | Thorsdottir, I.,Birgisdottir, B. E.,Johannsdottir, I. M.,Harris, D. P.,Hill, J.,Steingrimsdottir, L.,Thorsson, A. V. (2000). Different beta-casein fractions in Icelandic versus Scandinavian cow’s milk may influence diabetogenicity of cow’s milk in infancy and explain low incidence of insulin-dependent diabetes mellitus in Iceland Pediatrics, 106(4), 719-24 | Outcome
2557 | Thorsdottir, I.,Gunnarsdottir, I.,Kvaran, M. A.,Gretarsson, S. J. (2005). Maternal body mass index, duration of exclusive breastfeeding and children’s development status at the age of 6 years European Journal of Clinical Nutrition, 59(3), 426-431 | Intervention/exposure
2558 | Thorsdottir, I.,Gunnarsdottir, I.,Kvaran, M. A.,Gretarsson, S. J. (2005). Maternal body mass index, duration of exclusive breastfeeding and children’s developmental status at the age of 6 years Eur J Clin Nutr, 59(3), 426-31 | Intervention/exposure
2559 | Thorsdottir, I.,Gunnarsdottir, I.,Palsson, G. I. (2003). Association of birth weight and breast-feeding with coronary heart disease risk factors at the age of 6 years Nutr Metab Cardiovasc Dis, 13(5), 267-72 | Outcome
2560 | Thorsdottir, I.,Gunnarsdottir, I.,Palsson, G. I. (2003). Birth weight, growth and feeding in infancy: relation to serum lipid concentration in 12-month-old infants Eur J Clin Nutr, 57(11), 1479-85 | Outcome
2561 | Thorsdottir, I.,Gunnarsson, B. S. (2006). Dietary quality and adequacy of micronutrient intakes in children Proc Nutr Soc, 65(4), 366-75 | Study design
2562 | Thurtle, V. (1985). Infant feeding Nurs Mirror, 160(19), 44-5 | Study design, Outcome
2563 | Timby, N.,Domellof, E.,Hernell, O.,Lonnerdal, B.,Domellof, M. (2014). Neurodevelopment, nutrition, and growth until 12 mo of age in infants fed a low-energy, low-protein formula supplemented with bovine milk fat globule membranes: a randomized controlled trial Am J Clin Nutr, 99(4), 860-8 | Intervention/exposure
2564 | Timby, N.,Hernell, O.,Lonnerdal, B.,Domellof, M. (2014). Parental feeding control in relation to feeding mode and growth pattern during early infancy Acta Paediatr, 103(10), 1072-7 | Intervention/exposure
2565 | Timby, N.,Hernell, O.,Vaarala, O.,Melin, M.,Lonnerdal, B.,Domellof, M. (2015). Infections in infants fed formula supplemented with bovine milk fat globule membranes J Pediatr Gastroenterol Nutr, 60(3), 384-9 | Intervention/exposure
2566 | Timby, N.,Lonnerdal, B.,Hernell, O.,Domellof, M. (2014). Cardiovascular risk markers until 12 mo of age in infants fed a formula supplemented with bovine milk fat globule membranes Pediatr Res, 76(4), 394-400 | Intervention/exposure
2567 | Timmermans, F. J.,Gerson, S. (1980). Chronic granulomatous otitis media in bottle-fed Inuit children Can Med Assoc J, 122(5), 545-7 | Study design, Intervention/exposure
2568 | Timmermans, M. J.,Dagnelie, P. C.,Theunisz, E. H.,Ewalds, D.,Thijs, C.,Mommers, M.,Arts, I. C. (2015). Dietary nucleotide and nucleoside exposure in infancy and atopic dermatitis, recurrent wheeze, and allergic sensitization J Pediatr Gastroenterol Nutr, 60(5), 691-3 | Intervention/exposure
2569 | Tiwari, S. (2015). Age of Introduction of Complementary Feeding and Iron Deficiency Anemia in Breastfed Infants,Child Health Viewpoint Indian Pediatr, 52(11), 977-8 | Study design
2570 | Todd, R.,Gelbier, S. (1990). Dental caries prevalence in Vietnamese children and teenagers in three London boroughs Br Dent J, 168(1), 24-6 | Study design
2571 | Togo, A.,Espadas Macia, D.,Blanes Segura, S.,Sivo Diaz, N.,Villalba Martinez, C. (2015). [Is there vitamin D deficiency in children in a sunny Mediterranean city?] An Pediatr (Barc), #volume#(#issue#), #Pages# | Study design, Intervention/exposure
2572 | Tom, W. L. (2012). Atopic dermatitis: Recent findings and insights Pediatric Annals, 41(1), 1-5 | Study design
2573 | Tomblin, J. B.,Smith, E.,Zhang, X. (1997). Epidemiology of specific language impairment: prenatal and perinatal risk factors J Commun Disord, 30(4), 325-43; quiz 343-4 | Outcome
2574 | Toms, G. L.,Scott, R. (1987). Respiratory syncytial virus and the infant immune response Arch Dis Child, 62(6), 544-6 | Study design, Intervention/exposure
2575 | Toro Monjaraz, E. M.,Ramirez Mayans, J. A.,Cervantes Bustamante, R.,Gomez Morales, E.,Molina Rosales, A.,Montijo Barrios, E.,Zarate Mondragon, F.,Cadena Leon, J.,Cazares Mendez, M.,Lopez-Ugalde, M. (2015). Perinatal factors associated with the development of cow’s milk protein allergy Rev Gastroenterol Mex, 80(1), 27-31 | Language
2576 | Toro, K.,Sotonyi, P. (2001). Distribution of prenatal and postnatal risk factors for sudden infant death in Budapest Scand J Prim Health Care, 19(3), 178-80 | Intervention/exposure
2577 | Torowicz, Deborah L.,Spatz, Diane L.,Seelhorst, Amanda (2013). Human Milk and Breastfeeding in the Cardiac Center: A Prospective, Descriptive Study Journal of Pediatric Healthcare, 27(5), 325-325 1p | Participant health, Publication status
2578 | Torsvik, I. K.,Markestad, T.,Ueland, P. M.,Nilsen, R. M.,Midttun, O.,Bjorke Monsen, A. L. (2013). Evaluating iron status and the risk of anemia in young infants using erythrocyte parameters Pediatr Res, 73(2), 214-20 | Size of study groups
2579 | Toschke, A. M.,Beyerlein, A.,von Kries, R. (2005). Children at high risk for overweight: a classification and regression trees analysis approach Obes Res, 13(7), 1270-4 | Study design
2580 | Toschke, A. M.,Martin, R. M.,von Kries, R.,Wells, J.,Smith, G. D.,Ness, A. R. (2007). Infant feeding method and obesity: body mass index and dual-energy X-ray absorptiometry measurements at 9-10 y of age from the Avon Longitudinal Study of Parents and Children (ALSPAC) Am J Clin Nutr, 85(6), 1578-85 | Outcome
2581 | Toselli, S.,Zaccagni, L.,Celenza, F.,Albertini, A.,Gualdi-Russo, E. (2015). Risk factors of overweight and obesity among preschool children with different ethnic background Endocrine, 49(3), 717-25 | Study design
2582 | Tozzi, A. E.,Bisiacchi, P.,Tarantino, V.,Chiarotti, F.,D’Elia, L.,De Mei, B.,Romano, M.,Gesualdo, F.,Salmaso, S. (2012). Effect of duration of breastfeeding on neuropsychological development at 10 to 12 years of age in a cohort of healthy children Dev Med Child Neurol, 54(9), 843-8 | Intervention/exposure
2583 | Trabulsi, J.,Capeding, R.,Lebumfacil, J.,Ramanujam, K.,Feng, P.,McSweeney, S.,Harris, B.,DeRusso, P. (2011). Effect of an alpha-lactalbumin-enriched infant formula with lower protein on growth Eur J Clin Nutr, 65(2), 167-74 | Outcome
2584 | Tran, T. D.,Biggs, B. A.,Tran, T.,Simpson, J. A.,Hanieh, S.,Dwyer, T.,Fisher, J. (2013). Impact on infants’ cognitive development of antenatal exposure to iron deficiency disorder and common mental disorders PLoS One, 8(9), e74876 | Country, Intervention/exposure
2585 | Trapp, P. G.,Mielke, J. H.,Jorde, L. B.,Eriksson, A. W. (1983). Infant mortality patterns in Aland, Finland Hum Biol, 55(1), 131-49 | Study design, Intervention/exposure
2586 | Trevino-Garza, C.,Mancillas-Adame, L.,Villarreal-Perez, J. Z.,De la, O. Cavazos M. E.,Estrada-Zuniga, C. M.,Bosques-Padilla, F. J.,Argente, J. (2012). Association between umbilical cord leptin and weight gain according to feeding type in the early postnatal period, a brief report Rev Invest Clin, 64(6 Pt 2), 615-9 | Outcome
2587 | Truswell, A. S. (1985). ABC of nutrition. Infant feeding Br Med J (Clin Res Ed), 291(6491), 333-7 | Study design
2588 | Tsai, A. I.,Johnsen, D. C.,Lin, Y. H.,Hsu, K. H. (2001). A study of risk factors associated with nursing caries in Taiwanese children aged 24-48 months Int J Paediatr Dent, 11(2), 147-9 | Study design
2589 | Tsai, S. F.,Chen, S. J.,Yen, H. J.,Hung, G. Y.,Tsao, P. C.,Jeng, M. J.,Lee, Y. S.,Soong, W. J.,Tang, R. B. (2014). Iron deficiency anemia in predominantly breastfed young children Pediatr Neonatol, 55(6), 466-9 | Study design, Participant health
2590 | Tsang RC (1983). The quandary of vitamin D in the newborn infant Lancet, 1(#issue#), 1370-2 | Study design
2591 | Tsao, P. C.,Chang, F. Y.,Chen, S. J.,Soong, W. J.,Jeng, M. J.,Lee, Y. S.,Yen, H. J.,Yang, C. F.,Tang, R. B. (2012). Sudden and unexpected and near death during the early neonatal period: a multicenter study J Chin Med Assoc, 75(2), 65-9 | Study design, Size of study groups
2592 | Tse, S. M.,Coull, B. A.,Sordillo, J. E.,Datta, S.,Gold, D. R. (2015). Gender- and age-specific risk factors for wheeze from birth through adolescence Pediatric Pulmonology, 50(10), 955-962 | Outcome
2593 | Tseng, E.,Potter, S. M.,Picciano, M. F. (1990). Dietary protein source and plasma lipid profiles of infants Pediatrics, 85(4), 548-52 | Size of study groups
2594 | Tsubouchi, J.,Higashi, T.,Shimono, T.,Domoto, P. K.,Weinstein, P. (1994). A study of baby bottle tooth decay and risk factors for 18-month old infants in rural Japan ASDC J Dent Child, 61(4), 293-8 | Study design
2595 | Tsubouchi, J.,Tsubouchi, M.,Maynard, R. J.,Domoto, P. K.,Weinstein, P. (1995). A study of dental caries and risk factors among Native American infants ASDC J Dent Child, 62(4), 283-7 | Study design
2596 | Tsutie S,Kurihara N,Sasaki A,Takagi A,Seguti H,Inatome T (2010). Formulas providing adequate pantothenic acid, vitamin D, manganese, iron and vitamin A for infants fed with mother’s milk (aged 6-11 months) according to the Japanese Dietary Reference Intakes prepared by the Ministry of Health, Labour and Welfare (2005 edition) Matern Child Nutr, 6(#issue#), 147-58 | Intervention/exposure, Outcome
2597 | Tu, P. (1989). The effects of breastfeeding and birth spacing on child survival in China Stud Fam Plann, 20(6 Pt 1), 332-42 | Study design
2598 | Tulldahl, J.,Pettersson, K.,Andersson, S. W.,Hulthen, L. (1999). Mode of infant feeding and achieved growth in adolescence: early feeding patterns in relation to growth and body composition in adolescence Obes Res, 7(5), 431-7 | Intervention/exposure
2599 | Tuncbilek, E.,Uner, S.,Ulusoy, M. (1983). Breastfeeding in Turkey: the demographic and socio-economic aspects and relationship with infant/child mortality Turk J Pediatr, 25(1), 3-23 | Study design, Outcome
2600 | Turati, F.,Bertuccio, P.,Galeone, C.,Pelucchi, C.,Naldi, L.,Bach, J. F.,La Vecchia, C.,Chatenoud, L. (2016). Early weaning is beneficial to prevent atopic dermatitis occurrence in young children Allergy, #volume#(#issue#), #Pages# | Outcome
2601 | Turck, D.,Grillon, C.,Lachambre, E.,Robiliard, P.,Beck, L.,Maurin, J. L.,Kempf, C.,Bernet, J. P.,Marx, J.,Lebrun, F.,Van Egroo, L. D. (2006). Adequacy and safety of an infant formula with a protein/energy ratio of 1.8 g/100 kcal and enhanced protein efficiency for term infants during the first 4 months of life J Pediatr Gastroenterol Nutr, 43(3), 364-71 | Intervention/exposure
2602 | Turkoglu, S.,Bilgic, A.,Akca, O. F. (2015). ADHD symptoms, breast-feeding and obesity in children and adolescents Pediatr Int, 57(4), 546-51 | Study design
2603 | Turner, S.,Zhang, G.,Young, S.,Cox, M.,Goldblatt, J.,Landau, L.,Le Souef, P. (2008). Associations between postnatal weight gain, change in postnatal pulmonary function, formula feeding and early asthma Thorax, 63(3), 234-9 | Intervention/exposure
2604 | Tuthill, D. P.,Cosgrove, M.,Dunstan, F.,Stuart, M. L.,Wells, J. C.,Davies, D. P. (2002). Randomized double-blind controlled trial on the effects on iron status in the first year between a no added iron and standard infant formula received for three months Acta Paediatr, 91(2), 119-24 | Intervention/exposure
2605 | Tyler, M.,Hellings, P. (2005). Feeding method and rehospitalization in newborns less than 1 month of age J Obstet Gynecol Neonatal Nurs, 34(1), 70-9 | Participant health, Size of study groups
2606 | Tyson, J.,Burchfield, J.,Sentance, F.,Mize, C.,Uauy, R.,Eastburn, J. (1992). Adaptation of feeding to a low fat yield in breast milk Pediatrics, 89(2), 215-20 | Intervention/exposure, Size of study groups
2607 | Uauy, R.,Mize, C. E.,Castillo-Duran, C. (2000). Fat intake during childhood: metabolic responses and effects on growth Am J Clin Nutr, 72(5 Suppl), 1354S-1360S | Study design, Size of study groups
2608 | Ugur, S.,Haktan, M.,Cakir, E.,Senocak, M.,Telci, A. (1988). Serum insulin and blood glucose levels in breast-fed and formula-fed infants in the first week of life Clin Ther, 10(6), 678-87 | Study design, Size of study groups
2609 | Uhl, O.,Hellmuth, C.,Demmelmair, H.,Zhou, S. J.,Makrides, M.,Prosser, C.,Lowry, D.,Gibson, R. A.,Koletzko, B. (2015). Dietary Effects on Plasma Glycerophospholipids J Pediatr Gastroenterol Nutr, 61(3), 367-72 | Outcome
2610 | Uijterschout, L.,Vloemans, J.,Vos, R.,Teunisse, P. P.,Hudig, C.,Bubbers, S.,Verbruggen, S.,Veldhorst, M.,De Leeuw, T.,Van Goudoever, J. B.,Brus, F. (2014). Prevalence and risk factors of iron deficiency in healthy young children in the southwestern netherlands Journal of Pediatric Gastroenterology and Nutrition, 58(2), 193-198 | Study design
2611 | Ulak, M.,Chandyo, R. K.,Adhikari, R. K.,Sharma, P. R.,Sommerfelt, H.,Refsum, H.,Strand, T. A. (2014). Cobalamin and folate status in 6 to 35 months old children presenting with acute diarrhea in Bhaktapur, Nepal PLoS One, 9(3), e90079 | Country
2612 | Ulbak, J.,Lauritzen, L.,Hansen, H. S.,Michaelsen, K. F. (2004). Diet and blood pressure in 2.5-y-old Danish children Am J Clin Nutr, 79(6), 1095-102 | Outcome
2613 | Umer, A.,Hamilton, C.,Britton, C. M.,Mullett, M. D.,John, C.,Neal, W.,Lilly, C. L. (2015). Association between Breastfeeding and Childhood Obesity: Analysis of a Linked Longitudinal Study of Rural Appalachian Fifth-Grade Children Child Obes, 11(4), 449-55 | Study design
2614 | Unay, B.,Sarici, S. U.,Ulas, U. H.,Akin, R.,Alpay, F.,Gokcay, E. (2004). Nutritional effects on auditory brainstem maturation in healthy term infants Arch Dis Child Fetal Neonatal Ed, 89(2), F177-9 | Size of study groups
2615 | Urayama, K. Y.,Chokkalingam, A. P.,Metayer, C.,Ma, X.,Selvin, S.,Barcellos, L. F.,Wiemels, J. L.,Wiencke, J. K.,Taylor, M.,Brennan, P.,Dahl, G. V.,Moonsamy, P.,Erlich, H. A.,Trachtenberg, E.,Buffler, P. A. (2012). HLA-DP genetic variation, proxies for early life immune modulation and childhood acute lymphoblastic leukemia risk Blood, 120(15), 3039-47 | Outcome
2616 | Vaarala, O.,Ilonen, J.,Ruohtula, T.,Pesola, J.,Virtanen, S. M.,Harkonen, T.,Koski, M.,Kallioinen, H.,Tossavainen, O.,Poussa, T.,Jarvenpaa, A. L.,Komulainen, J.,Lounamaa, R.,Akerblom, H. K.,Knip, M. (2012). Removal of bovine insulin from cow’s milk formula and early initiation of beta-cell autoimmunity in the FINDIA pilot study Archives of pediatrics & adolescent medicine, 166(7), 608-14 | Size of study groups, Intervention/exposure
2617 | Vaarala, O.,Knip, M.,Paronen, J.,Hamalainen, A. M.,Muona, P.,Vaatainen, M.,Ilonen, J.,Simell, O.,Akerblom, H. K. (1999). Cow’s milk formula feeding induces primary immunization to insulin in infants at genetic risk for type 1 diabetes Diabetes, 48(7), 1389-94 | Outcome
2618 | Vafa, M.,Heshmati, J.,Sadeghi, H.,Shidfar, F.,Namazi, N.,Baradaran, H.,Heydarpour, B.,Jalili, Z. (2015). Is exclusive breastfeeding and its duration related to cardio respiratory fitness in childhood? J Matern Fetal Neonatal Med, #volume#(#issue#), 1-6 | Study design
2619 | Vaidergorn, B. (1991). Oral habits and atypical deglutition in certain Sao Paulo children Int J Orofacial Myology, 17(3), 11-5 | Study design, Intervention/exposure
2620 | Valaitis, R. K.,Ciliska, D. K.,Sheeshka, J. D.,Sword, W. A. (1996). Surveying infant feeding practices Can Nurse, 92(4), 21 | Study design
2621 | Valentin-Blasini, L.,Blount, B. C.,Otero-Santos, S.,Cao, Y.,Bernbaum, J. C.,Rogan, W. J. (2011). Perchlorate exposure and dose estimates in infants Environ Sci Technol, 45(9), 4127-32 | Study design
2622 | Valman, H. B. (1980). The first year of life: feeding and feeding problems Br Med J, 280(6212), 457-60 | Study design
2623 | Valvi, D.,Mendez, M. A.,Garcia-Esteban, R.,Ballester, F.,Ibarluzea, J.,Goni, F.,Grimalt, J. O.,Llop, S.,Marina, L. S.,Vizcaino, E.,Sunyer, J.,Vrijheid, M. (2014). Prenatal exposure to persistent organic pollutants and rapid weight gain and overweight in infancy Obesity (Silver Spring), 22(2), 488-96 | Intervention/exposure
2624 | Van Asperen, P. P.,Kemp, A. S.,Mellis, C. M. (1984). Relationship of diet in the development of atopy in infancy Clin Allergy, 14(6), 525-32 | Intervention/exposure, Size of study groups
2625 | van Beijsterveldt, T. C.,Boomsma, D. I. (2008). An exploration of gene-environment interaction and asthma in a large sample of 5-year-old Dutch twins Twin Res Hum Genet, 11(2), 143-9 | Outcome
2626 | Van Biervliet, J. P.,Rosseneu, M.,Caster, H. (1986). Influence of dietary factors on the plasma lipoprotein composition and content in neonates Eur J Pediatr, 144(5), 489-93 | Size of study groups
2627 | Van Biervliet, J. P.,Vinaimont, N.,Caster, H.,Vercaemst, R.,Rosseneu, M. (1981). Lipoprotein patterns in newborns. Influence of nutritional factors Acta Cardiol Suppl, 27(#issue#), 69-81 | Size of study groups
2628 | van Biervliet, J. P.,Vinaimont, N.,Caster, H.,Vercaemst, R.,Rosseneu, M. (1981). Plasma apoprotein and lipid patterns in newborns: influence of nutritional factors Acta Paediatr Scand, 70(6), 851-6 | Size of study groups
2629 | Van Biervliet, J. P.,Vinaimont, N.,Vercaemst, R.,Rosseneu, M. (1992). Serum cholesterol, cholesteryl ester, and high-density lipoprotein development in newborn infants: response to formulas supplemented with cholesterol and gamma-linolenic acid J Pediatr, 120(4 Pt 2), S101-8 | Size of study groups
2630 | Van Biervliet, S.,Van Biervliet, J. P.,Bernard, D.,Vercaemst, R.,Blaton, V. (2003). Serum zinc in healthy Belgian children Biological Trace Element Research, 94(1), 33-40 | Study design
2631 | van Buuren, S. (2010). Effects of selective dropout on infant growth standards Nestle Nutr Workshop Ser Pediatr Program, 65(#issue#), 167-75; discussion 175-9 | Publication status
2632 | van den Berg, G.,van Eijsden, M.,Galindo-Garre, F.,Vrijkotte, T. G.,Gemke, R. J. (2013). Explaining socioeconomic inequalities in childhood blood pressure and prehypertension: the ABCD study Hypertension, 61(1), 35-41 | Intervention/exposure
2633 | Van Den Berg, G.,Van Eijsden, M.,Galindo-Garre, F.,Vrijkotte, T.,Gemke, R. (2013). Low maternal education is associated with increased growth velocity in the first year of life and in early childhood: the ABCD study Eur J Pediatr, 172(11), 1451-7 | Intervention/exposure
2634 | van den Bogaard, C.,van den Hoogen, H. J.,Huygen, F. J.,van Weel, C. (1991). The relationship between breast-feeding and early childhood morbidity in a general population Fam Med, 23(7), 510-5 | Study design
2635 | van den Bogaard, C.,van den Hoogen, H. J.,Huygen, F. J.,van Weel, C. (1993). Is the breast best for children with a family history of atopy? The relation between way of feeding and early childhood morbidity Fam Med, 25(7), 471-5 | Intervention/exposure
2636 | Van der Elst, C. W.,Dempster, W. S.,Woods, D. L.,Heese, H. D. (1986). Serum zinc and copper in thin mothers, their breast milk and their infants J Trop Pediatr, 32(3), 111-4 | Country, Intervention/exposure
2637 | van der Willik, E. M.,Vrijkotte, T. G.,Altenburg, T. M.,Gademan, M. G.,Kist-van Holthe, J. (2015). Exclusively breastfed overweight infants are at the same risk of childhood overweight as formula fed overweight infants Arch Dis Child, 100(10), 932-7 | Intervention/exposure
2638 | van Dijk, C. E.,Innis, S. M. (2009). Growth-curve standards and the assessment of early excess weight gain in infancy Pediatrics, 123(1), 102-8 | Size of study groups, Intervention/exposure
2639 | van Elten, T. M.,van Rossem, L.,Wijga, A. H.,Brunekreef, B.,de Jongste, J. C.,Koppelman, G. H.,Smit, H. A. (2015). Breast milk fatty acid composition has a long-term effect on the risk of asthma, eczema, and sensitization Allergy, 70(11), 1468-76 | Intervention/exposure
2640 | Van Howe, R. S.,Storms, M. R. (2008). Blood glucose determinations in large for gestational age infants Am J Perinatol, 25(5), 283-9 | Study design, Intervention/exposure
2641 | van Merode, T.,Maas, T.,Twellaar, M.,Kester, A.,van Schayck, C. P. (2007). Gender-specific differences in the prevention of asthma-like symptoms in high-risk infants Pediatr Allergy Immunol, 18(3), 196-200 | Outcome
2642 | van Odijk, J.,Hulthen, L.,Ahlstedt, S.,Borres, M. P. (2004). Introduction of food during the infant’s first year: a study with emphasis on introduction of gluten and of egg, fish and peanut in allergy-risk families Acta Paediatr, 93(4), 464-70 | Study design, Intervention/exposure
2643 | van Palenstein Helderman, W. H.,Soe, W.,van ’t Hof, M. A. (2006). Risk factors of early childhood caries in a Southeast Asian population J Dent Res, 85(1), 85-8 | Country, Intervention/exposure
2644 | van Rossem, L.,Taveras, E. M.,Gillman, M. W.,Kleinman, K. P.,Rifas-Shiman, S. L.,Raat, H.,Oken, E. (2011). Is the association of breastfeeding with child obesity explained by infant weight change? Int J Pediatr Obes, 6(2-2), e415-22 | Outcome
2645 | van Rossem, L.,Wijga, A. H.,Brunekreef, B.,de Jongste, J. C.,Kerkhof, M.,Postma, D. S.,Gehring, U.,Smit, H. A. (2014). Overweight in infancy: which pre- and perinatal factors determine overweight persistence or reduction? A birth cohort followed for 11 years Ann Nutr Metab, 65(2-3), 211-9 | Participant health
2646 | van Rossem, L.,Wijga, A. H.,de Jongste, J. C.,Koppelman, G. H.,Oldenwening, M.,Postma, D. S.,Abrahamse-Berkeveld, M.,van de Heijning, B.,Brunekreef, B.,Smit, H. A. (2012). Blood pressure in 12-year-old children is associated with fatty acid composition of human milk: the prevention and incidence of asthma and mite allergy birth cohort Hypertension, 60(4), 1055-60 | Intervention/exposure
2647 | van Stuijvenberg, M.,Eisses, A. M.,Gruber, C.,Mosca, F.,Arslanoglu, S.,Chirico, G.,Braegger, C. P.,Riedler, J.,Boehm, G.,Sauer, P. J. (2011). Do prebiotics reduce the number of fever episodes in healthy children in their first year of life: a randomised controlled trial Br J Nutr, 106(11), 1740-8 | Intervention/exposure
2648 | van Stuijvenberg, M.,Stam, J.,Gruber, C.,Mosca, F.,Arslanoglu, S.,Chirico, G.,Braegger, C. P.,Riedler, J.,Boehm, G.,Sauer, P. J. (2015). Similar Occurrence of Febrile Episodes Reported in Non-Atopic Children at Three to Five Years of Age after Prebiotics Supplemented Infant Formula PLoS One, 10(6), e0129927 | Intervention/exposure
2649 | van t Hof Msc, M. A. (2000). The influence of breastfeeding and complementary foods on growth until three years of age in the Euro-Growth Study Pediatrics, 106(5), 1281a-1281 | Intervention/exposure
2650 | van Wouwe, J. P.,van den Hamer, C. J.,van Tricht, J. B. (1986). Serum zinc concentrations in exclusively breast-fed infants and in infants fed an adapted formula Eur J Pediatr, 144(6), 598-600 | Study design
2651 | Vandenplas, Y.,Deneyer, M.,Sacre, L.,Loeb, H. (1988). Preliminary data on a field study with a new hypo-allergic formula European Journal of Pediatrics, 148(3), 274-277 | Size of study groups
2652 | Vandenplas, Y.,Sacre, L. (1986). Influences of neonatal serum IgE concentration, family history and diet on the incidence of cow’s milk allergy Eur J Pediatr, 145(6), 493-5 | Intervention/exposure
2653 | Vanderhoof, J. A.,Murray, N. D.,Antonson, D. L.,Kaufman, S. S. (1986). Familial occurrence of protracted diarrhea of infancy J Pediatr, 109(5), 845-7 | Study design, Size of study groups
2654 | Vanella, L.,de Gonzalez Lascano, A. M. (1988). CD4+, CD8+ cells, IgE and prick test in infants allergic to cow’s milk Allergol Immunopathol (Madr), 16(5), 327-31 | Participant health
2655 | Vanessa Nazareth, Isis,Maria Meneses dos Santos, InÃªs,Paula Oliveira GonÃ§alves, Ana,Sena Souza, Ester (2013). RISK FOR CHILD DEVELOPMENT ACCORDING TO THE INTEGRATED ATTENTION STRATEGY TO THE PREVALENT ILLNESSES IN CHILDHOOD Journal of Nursing UFPE / Revista de Enfermagem UFPE, 7(2), 328-336 9p | Study design, Intervention/exposure
2656 | Varga, G. (2008). A comparative study of the social-political determinants of infant and child mortality in Sweden and Hungary 1850-1945 Orvostort Kozl, 54(1-4), 5-29 | Study design
2657 | Vasallo, M. I.,Martinez, R.,Ballesta, M. J.,Vives, I.,Sanchez-Solis, M.,Peso, P.,Martinez, C. (2011). Effect of an infant formula containing milk fat, Alpha-lactalbumin, Nucleotides and lcpufa on stool patterns in infants Journal of pediatric gastroenterology and nutrition, 52(#issue#), E166 | Publication status
2658 | Vazquez, E. (2007). 14th annual retrovirus conference (CROI). Astounding choice in breastfeeding: infection or death Posit Aware, 18(3), 29-30 | Study design
2659 | Veereman-Wauters, G.,Staelens, S.,Van de Broek, H.,Plaskie, K.,Wesling, F.,Roger, L. C.,McCartney, A. L.,Assam, P. (2011). Physiological and bifidogenic effects of prebiotic supplements in infant formulae J Pediatr Gastroenterol Nutr, 52(6), 763-71 | Size of study groups
2660 | Vehapoglu, A.,Yazici, M.,Demir, A. D.,Turkmen, S.,Nursoy, M.,Ozkaya, E. (2014). Early infant feeding practice and childhood obesity: the relation of breast-feeding and timing of solid food introduction with childhood obesity J Pediatr Endocrinol Metab, 27(11-12), 1181-7 | Study design
2661 | Venkataraman, P. S.,Luhar, H.,Neylan, M. J. (1992). Bone mineral metabolism in full-term infants fed human milk, cow milk-based, and soy-based formulas Am J Dis Child, 146(11), 1302-5 | Size of study groups
2662 | Vennemann, M.,Bajanowski, T.,Butterfass-Bahloul, T.,Sauerland, C.,Jorch, G.,Brinkmann, B.,Mitchell, E. A. (2007). Do risk factors differ between explained sudden unexpected death in infancy and sudden infant death syndrome? Arch Dis Child, 92(2), 133-6 | Outcome
2663 | Venter, C.,Pereira, B.,Voigt, K.,Grundy, J.,Clayton, C. B.,Higgins, B.,Arshad, S. H.,Dean, T. (2009). Factors associated with maternal dietary intake, feeding and weaning practices, and the development of food hypersensitivity in the infant Pediatr Allergy Immunol, 20(4), 320-7 | Intervention/exposure
2664 | Ventura, A. K.,Loken, E.,Birch, L. L. (2009). Developmental trajectories of girls’ BMI across childhood and adolescence Obesity (Silver Spring), 17(11), 2067-74 | Outcome
2665 | Ventura, A.,Longo, G.,Longo, F.,Florean, P.,Scornavacca, G. (1989). Diet and atopic eczema in children Allergy, 44 Suppl 9(#issue#), 159-64 | Study design, Size of study groups
2666 | Verga, M. E.,Widmeier-Pasche, V.,Beck-Popovic, M.,Pauchard, J. Y.,Gehri, M. (2014). Iron deficiency in infancy: is an immigrant more at risk? Swiss Med Wkly, 144(#issue#), w14065 | Study design, Intervention/exposure
2667 | Verge, C. F.,Howard, N. J.,Irwig, L.,Simpson, J. M.,Mackerras, D.,Silink, M. (1994). Environmental factors in childhood IDDM. A population-based, case-control study Diabetes Care, 17(12), 1381-9 | Outcome
2668 | Verkasalo, M.,Kuitunen, P.,Savilahti, E.,Tiilikainen, A. (1981). Changing pattern of cow’s milk intolerance. An analysis of the occurrence and clinical course in the 60s and mid-70s Acta Paediatr Scand, 70(3), 289-95 | Participant health, Intervention/exposure
2669 | Vernacchio, L.,Lesko, S. M.,Vezina, R. M.,Corwin, M. J.,Hunt, C. E.,Hoffman, H. J.,Mitchell, A. A. (2004). Racial/ethnic disparities in the diagnosis of otitis media in infancy Int J Pediatr Otorhinolaryngol, 68(6), 795-804 | Study design
2670 | Verstraete, S. G.,Heyman, M. B.,Wojcicki, J. M. (2014). Breastfeeding offers protection against obesity in children of recently immigrated Latina women J Community Health, 39(3), 480-6 | Outcome
2671 | Vesel, L.,Bahl, R.,Martines, J.,Penny, M.,Bhandari, N.,Kirkwood, B. R. (2010). Use of new World Health Organization child growth standards to assess how infant malnutrition relates to breastfeeding and mortality Bull World Health Organ, 88(1), 39-48 | Intervention/exposure
2672 | Vesikari, T.,Prymula, R.,Schuster, V.,Tejedor, J. C.,Cohen, R.,Bouckenooghe, A.,Damaso, S.,Han, H. H. (2012). Efficacy and immunogenicity of live-attenuated human rotavirus vaccine in breast-fed and formula-fed European infants Pediatr Infect Dis J, 31(5), 509-13 | Outcome
2673 | Vestergaard, M.,Obel, C.,Henriksen, T. B.,Sorensen, H. T.,Skajaa, E.,Ostergaard, J. (1999). Duration of breastfeeding and developmental milestones during the latter half of infancy Acta Paediatr, 88(12), 1327-32 | Outcome
2674 | Vestman, N. R.,Timby, N.,Holgerson, P. L.,Kressirer, C. A.,Claesson, R.,Domellof, M.,Ohman, C.,Tanner, A. C.,Hernell, O.,Johansson, I. (2013). Characterization and in vitro properties of oral lactobacilli in breastfed infants BMC Microbiol, 13(#issue#), 193 | Study design
2675 | Vichyanond, P. (1990). IgE regulation and the control of allergic diseases Asian Pac J Allergy Immunol, 8(1), 1-4 | Study design
2676 | Victora, C. G.,Barros, F. C.,Horta, B. L.,Lima, R. C. (2005). Breastfeeding and school achievement in Brazilian adolescents Acta Paediatr, 94(11), 1656-60 | Outcome
2677 | Victora, C. G.,Barros, F.,Lima, R. C.,Horta, B. L.,Wells, J. (2003). Anthropometry and body composition of 18 year old men according to duration of breast feeding: birth cohort study from Brazil BMJ, 327(7420), 901 | Outcome
2678 | Victora, C. G.,Fuchs, S. C.,Flores, J. A.,Fonseca, W.,Kirkwood, B. (1994). Risk factors for pneumonia among children in a Brazilian metropolitan area Pediatrics, 93(6 Pt 1), 977-85 | Intervention/exposure
2679 | Victora, C. G.,Hallal, P. C.,Araújo, C. L. P.,Menezes, A. M. B.,Wells, J. C. K.,Barros, F. C. (2008). Cohort profile: The 1993 pelotas (Brazil) birth cohort study International Journal of Epidemiology, 37(4), 704-709 | Study design
2680 | Victora, C. G.,Horta, B. L.,Loret de Mola, C.,Quevedo, L.,Pinheiro, R. T.,Gigante, D. P.,Goncalves, H.,Barros, F. C. (2015). Association between breastfeeding and intelligence, educational attainment, and income at 30 years of age: a prospective birth cohort study from Brazil Lancet Glob Health, 3(4), e199-205 | Outcome
2681 | Victora, C. G.,Horta, B. L.,Post, P.,Lima, R. C.,De Leon Elizalde, J. W.,Gerson, B. M.,Barros, F. C. (2006). Breast feeding and blood lipid concentrations in male Brazilian adolescents J Epidemiol Community Health, 60(7), 621-5 | Outcome
2682 | Victora, C. G.,Huttly, S. R.,Barros, F. C.,Martines, J. C.,Vaughan, J. P. (1991). Prolonged breastfeeding and malnutrition: confounding and effect modification in a Brazilian cohort study Epidemiology, 2(3), 175-81 | Outcome
2683 | Victora, C. G.,Huttly, S. R.,Fuchs, S. C.,Nobre, L. C.,Barros, F. C. (1992). Deaths due to dysentery, acute and persistent diarrhoea among Brazilian infants Acta Paediatr Suppl, 381(#issue#), 7-11 | Study design
2684 | Victora, C. G.,Morris, S. S.,Barros, F. C.,de Onis, M.,Yip, R. (1998). The NCHS reference and the growth of breast- and bottle-fed infants J Nutr, 128(7), 1134-8 | Intervention/exposure
2685 | Victora, C. G.,Morris, S. S.,Barros, F. C.,Horta, B. L.,Weiderpass, E.,Tomasi, E. (1998). Breast-feeding and growth in Brazilian infants Am J Clin Nutr, 67(3), 452-8 | Intervention/exposure
2686 | Victora, C. G.,Rivera, J. A. (2014). Optimal child growth and the double burden of malnutrition: Research and programmatic implications American Journal of Clinical Nutrition, 100(6), 1611S-1612S | Study design
2687 | Victora, C. G.,Smith, P. G.,Barros, F. C.,Vaughan, J. P.,Fuchs, S. C. (1989). Risk factors for deaths due to respiratory infections among Brazilian infants Int J Epidemiol, 18(4), 918-25 | Outcome
2688 | Victora, C. G.,Smith, P. G.,Vaughan, J. P.,Nobre, L. C.,Lombardi, C.,Teixeira, A. M.,Fuchs, S. C.,Moreira, L. B.,Gigante, L. P.,Barros, F. C. (1989). Infant feeding and deaths due to diarrhea. A case-control study Am J Epidemiol, 129(5), 1032-41 | Outcome
2689 | Victora, C. G.,Smith, P. G.,Vaughan, J. P.,Nobre, L. C.,Lombardi, C.,Teixeira, A. M.,Fuchs, S. M.,Moreira, L. B.,Gigante, L. P.,Barros, F. C. (1987). Evidence for protection by breast-feeding against infant deaths from infectious diseases in Brazil Lancet, 2(8554), 319-22 | Outcome
2690 | Victora, C. G.,Vaughan, J. P.,Martines, J. C.,Barcelos, L. B. (1984). Is prolonged breast-feeding associated with malnutrition? Am J Clin Nutr, 39(2), 307-14 | Study design
2691 | Viggiano, D.,Fasano, D.,Monaco, G.,Strohmenger, L. (2004). Breast feeding, bottle feeding, and non-nutritive sucking; effects on occlusion in deciduous dentition Arch Dis Child, 89(12), 1121-3 | Study design
2692 | Vigi, V.,Chierici, R.,Osti, L.,Fagioli, F.,Rescazzi, R. (1984). Serum zinc concentration in exclusively breast-fed infants and in infants fed an adapted formula Eur J Pediatr, 142(4), 245-7 | Size of study groups
2693 | Vignerova, J.,Shriver, L.,Paulova, M.,Brabec, M.,Schneidrova, D.,Ruzkova, R.,Prochazka, B.,Riedlovia, J. (2015). Growth of Czech breastfed infants in comparison with the World Health Organization standards Cent Eur J Public Health, 23(1), 32-8 | Intervention/exposure
2694 | Villalpando, S. (2000). Feeding mode, infections, and anthropometric status in early childhood Pediatrics, 106(5), 1282-3 | Study design
2695 | Villalpando, S.,Lopez-Alarcon, M. (2000). Growth faltering is prevented by breast-feeding in underprivileged infants from Mexico City J Nutr, 130(3), 546-52 | Outcome
2696 | Viner, R. M.,Hindmarsh, P. C.,Taylor, B.,Cole, T. J. (2008). Childhood body mass index (BMI), breastfeeding and risk of Type 1 diabetes: findings from a longitudinal national birth cohort Diabet Med, 25(9), 1056-61 | Intervention/exposure
2697 | Violato, M.,Petrou, S.,Gray, R.,Redshaw, M. (2011). Family income and child cognitive and behavioural development in the United Kingdom: does money matter? Health Econ, 20(10), 1201-25 | Study design, Intervention/exposure
2698 | Virtanen, S. M.,Kenward, M. G.,Erkkola, M.,Kautiainen, S.,Kronberg-Kippila, C.,Hakulinen, T.,Ahonen, S.,Uusitalo, L.,Niinisto, S.,Veijola, R.,Simell, O.,Ilonen, J.,Knip, M. (2006). Age at introduction of new foods and advanced beta cell autoimmunity in young children with HLA-conferred susceptibility to type 1 diabetes Diabetologia, 49(7), 1512-21 | Intervention/exposure, Outcome
2699 | Virtanen, S. M.,Rasanen, L.,Aro, A.,Lindstrom, J.,Sippola, H.,Lounamaa, R.,Toivanen, L.,Tuomilehto, J.,Akerblom, H. K. (1991). Infant feeding in Finnish children less than 7 yr of age with newly diagnosed IDDM. Childhood Diabetes in Finland Study Group Diabetes Care, 14(5), 415-7 | Outcome
2700 | Virtanen, S. M.,Rasanen, L.,Aro, A.,Ylonen, K.,Lounamaa, R.,Tuomilehto, J.,Akerblom, H. K. (1992). Feeding in infancy and the risk of type 1 diabetes mellitus in Finnish children. The ‘Childhood Diabetes in Finland’ Study Group Diabet Med, 9(9), 815-9 | Outcome
2701 | Virtanen, S. M.,Rasanen, L.,Ylonen, K.,Aro, A.,Clayton, D.,Langholz, B.,Pitkaniemi, J.,Savilahti, E.,Lounamaa, R.,Tuomilehto, J.,et al, (1993). Early introduction of dairy products associated with increased risk of IDDM in Finnish children. The Childhood in Diabetes in Finland Study Group Diabetes, 42(12), 1786-90 | Redundant data with another article
2702 | Virtanen, S. M.,Saukkonen, T.,Savilahti, E.,Ylonen, K.,Rasanen, L.,Aro, A.,Knip, M.,Tuomilehto, J.,Akerblom, H. K. (1994). Diet, cow’s milk protein antibodies and the risk of IDDM in Finnish children. Childhood Diabetes in Finland Study Group Diabetologia, 37(4), 381-7 | Outcome
2703 | Visalli, N.,Sebastiani, L.,Adorisio, E.,Conte, A.,De Cicco, A. L.,D’Elia, R.,Manfrini, S.,Pozzilli, P. (2003). Environmental risk factors for type 1 diabetes in Rome and province Arch Dis Child, 88(8), 695-8 | Outcome
2704 | Vithayasai, N.,Jennuvat, S. (2014). Persistent diarrhea: 15 years experience at a tertiary care hospital J Med Assoc Thai, 97 Suppl 6(#issue#), S95-100 | Participant health
2705 | Vitolo, M. R.,Bortolini, G. A.,Dal Bo Campagnolo, P.,Feldens, C. A. (2008). Effectiveness of a nutrition program in reducing symptoms of respiratory morbidity in children: a randomized field trial Prev Med, 47(4), 384-8 | Outcome
2706 | Vitolo, M. R.,Bortolini, G. A.,Feldens, C. A.,Drachler Mde, L. (2005). [Impacts of the 10 Steps to Healthy Feeding in Infants: a randomized field trial] Cadernos de saúde pública, 21(5), 1448-57 | Language
2707 | Vitolo, M. R.,da Costa Louzada, M. L.,Rauber, F.,Campagnolo, P. D. (2013). Risk factors for high blood pressure in low income children aged 3-4 years Eur J Pediatr, 172(8), 1097-103 | Outcome
2708 | Vivatvakin, B.,Mahayosnond, A.,Theamboonlers, A.,Steenhout, P. G.,Conus, N. J. (2010). Effect of a whey-predominant starter formula containing LCPUFAs and oligosaccharides (FOS/GOS) on gastrointestinal comfort in infants Asia Pac J Clin Nutr, 19(4), 473-80 | Outcome
2709 | Vobecky, J. S.,Vobecky, J.,Shapcott, D.,Demers, P. P. (1983). Nutrient intake patterns and nutritional status with regard to relative weight in early infancy Am J Clin Nutr, 38(5), 730-8 | Outcome
2710 | Vogazianos, E.,Vogazianos, P.,Fiala, J.,Janecek, D.,Slapak, I. (2007). The effect of breastfeeding and its duration on acute otitis media in children in Brno, Czech Republic Cent Eur J Public Health, 15(4), 143-6 | Study design
2711 | Volz, V. R.,Book, L. S.,Churella, H. R. (1983). Growth and plasma amino acid concentrations in term infants fed either whey-predominant formula or human milk J Pediatr, 102(1), 27-31 | Size of study groups
2712 | von Berg, A.,Koletzko, S.,Filipiak-Pittroff, B.,Laubereau, B.,Grubl, A.,Wichmann, H. E.,Bauer, C. P.,Reinhardt, D.,Berdel, D. (2007). Certain hydrolyzed formulas reduce the incidence of atopic dermatitis but not that of asthma: three-year results of the German Infant Nutritional Intervention Study J Allergy Clin Immunol, 119(3), 718-25 | Intervention/exposure
2713 | von Berg, A.,Koletzko, S.,Grubl, A.,Filipiak-Pittroff, B.,Wichmann, H. E.,Bauer, C. P.,Reinhardt, D.,Berdel, D. (2003). The effect of hydrolyzed cow’s milk formula for allergy prevention in the first year of life: the German Infant Nutritional Intervention Study, a randomized double-blind trial J Allergy Clin Immunol, 111(3), 533-40 | Intervention/exposure
2714 | von Kobyletzki, L. B.,Bornehag, C. G.,Hasselgren, M.,Larsson, M.,Lindstrom, C. B.,Svensson, A. (2012). Eczema in early childhood is strongly associated with the development of asthma and rhinitis in a prospective cohort BMC Dermatol, 12(#issue#), 11 | Outcome
2715 | von Linstow, M. L.,Hogh, M.,Nordbo, S. A.,Eugen-Olsen, J.,Koch, A.,Hogh, B. (2008). A community study of clinical traits and risk factors for human metapneumovirus and respiratory syncytial virus infection during the first year of life Eur J Pediatr, 167(10), 1125-33 | Intervention/exposure
2716 | von Mutius, E.,Hartert, T. (2013). Update in asthma 2012 Am J Respir Crit Care Med, 188(2), 150-6 | Study design
2717 | von Stumm, S.,Plomin, R. (2015). Breastfeeding and IQ Growth from Toddlerhood through Adolescence PLoS One, 10(9), e0138676 | Outcome
2718 | Vriezinga, S. L.,Auricchio, R.,Bravi, E.,Castillejo, G.,Chmielewska, A.,Crespo Escobar, P.,Kolacek, S.,Koletzko, S.,Korponay-Szabo, I. R.,Mummert, E.,Polanco, I.,Putter, H.,Ribes-Koninckx, C.,Shamir, R.,Szajewska, H.,Werkstetter, K.,Greco, L.,Gyimesi, J.,Hartman, C.,Hogen Esch, C.,Hopman, E.,Ivarsson, A.,Koltai, T.,Koning, F.,Martinez-Ojinaga, E.,te Marvelde, C.,Pavic, A.,Romanos, J.,Stoopman, E.,Villanacci, V.,Wijmenga, C.,Troncone, R.,Mearin, M. L. (2014). Randomized feeding intervention in infants at high risk for celiac disease N Engl J Med, 371(14), 1304-15 | Intervention/exposure
2719 | Wachs, T. D.,Kanashiro, H. C.,Gurkas, P. (2008). Intra-individual variability in infancy: structure, stability, and nutritional correlates Dev Psychobiol, 50(3), 217-31 | Intervention/exposure, Outcome
2720 | Wadsworth, E. J.,Shield, J. P.,Hunt, L. P.,Baum, J. D. (1997). A case-control study of environmental factors associated with diabetes in the under 5s Diabet Med, 14(5), 390-6 | Outcome
2721 | Wadsworth, M. E.,Hardy, R. J.,Paul, A. A.,Marshall, S. F.,Cole, T. J. (2002). Leg and trunk length at 43 years in relation to childhood health, diet and family circumstances; evidence from the 1946 national birth cohort Int J Epidemiol, 31(2), 383-90 | Intervention/exposure
2722 | Wagner, C. L.,Hulsey, T. C.,Fanning, D.,Ebeling, M.,Hollis, B. W. (2006). High-dose vitamin D3 supplementation in a cohort of breastfeeding mothers and their infants: a 6-month follow-up pilot study Breastfeed Med, 1(2), 59-70 | Intervention/exposure
2723 | Wagner, V.,von Stockhausen, H. B. (1988). The effect of feeding human milk and adapted milk formulae on serum lipid and lipoprotein levels in young infants Eur J Pediatr, 147(3), 292-5 | Study design
2724 | Wahlberg, J.,Vaarala, O.,Ludvigsson, J. (2006). Dietary risk factors for the emergence of type 1 diabetes-related autoantibodies in 21/2 year-old Swedish children Br J Nutr, 95(3), 603-8 | Outcome
2725 | Walker, W. A. (1994). Nucleotides and nutrition: role as dietary supplement J Nutr, 124(1 Suppl), 121s-123s | Study design, Intervention/exposure, Outcome
2726 | Wallis, J. (2012). Positive role of breastfeeding during the first six weeks Midwives, 15(3), 31 | Study design
2727 | Walshaw, C. A.,Owens, J. M.,Scally, A. J.,Walshaw, M. J. (2008). Does breastfeeding method influence infant weight gain? Arch Dis Child, 93(4), 292-6 | Intervention/exposure
2728 | Walter, T.,Pino, P.,Pizarro, F.,Lozoff, B. (1998). Prevention of iron-deficiency anemia: comparison of high- and low-iron formulas in term healthy infants after six months of life J Pediatr, 132(4), 635-40 | Intervention/exposure
2729 | Walton, J. L.,Messer, L. B. (1981). Dental caries and fluorosis in breast-fed and bottle-fed children Caries Res, 15(2), 124-37 | Study design
2730 | Waly, M. I.,Ali, A.,Al-Saadoon, M.,Al-Mukhaini, Y. K.,Wali, Y. A. (2011). Breastfeeding is not associated with risk of developing childhood leukemia in the Sultanate of Oman Asian Pac J Cancer Prev, 12(8), 2087-91 | Outcome
2731 | Wan, A. K.,Seow, W. K.,Purdie, D. M.,Bird, P. S.,Walsh, L. J.,Tudehope, D. I. (2001). Oral colonization of Streptococcus mutans in six-month-old predentate infants J Dent Res, 80(12), 2060-5 | Study design
2732 | Wandera, A. (1998). Anticipatory guidance in infant oral health J Mich Dent Assoc, 80(9), 28, 55-9 | Study design
2733 | Wang, H.,Wang, A.,Wang, D.,Bright, A.,Sency, V.,Zhou, A.,Xin, B. (2015). Early growth and development impairment in patients with ganglioside GM3 synthase deficiency Clin Genet, #volume#(#issue#), #Pages# | Participant health, Outcomes
2734 | Wang, I. J.,Guo, Y. L.,Hwang, K. C.,Hsieh, W. S.,Chuang, Y. L.,Lin, S. J.,Chen, P. C. (2006). Genetic and environmental predictors for pediatric atopic dermatitis Acta Paediatrica Taiwanica, 47(5), 238-242 | Study design
2735 | Wang, L.,Mamudu, H. M.,Alamian, A.,Anderson, J. L.,Brooks, B. (2014). Independent and joint effects of prenatal maternal smoking and maternal exposure to second-hand smoke on the development of adolescent obesity: a longitudinal study J Paediatr Child Health, 50(11), 908-15 | Intervention/exposure
2736 | Wang, X.,Xing, K. H.,Qi, J.,Guan, Y.,Zhang, J. (2013). Analysis of the relationship of insulin-like growth factor-1 to the growth velocity and feeding of healthy infants Growth Horm IGF Res, 23(6), 215-9 | Outcome
2737 | Wang, Y. F.,Ou-Yang, Q.,Xia, B.,Liu, L. N.,Gu, F.,Zhou, K. F.,Mei, Q.,Shi, R. H.,Ran, Z. H.,Wang, X. D.,Hu, P. J.,Wu, K. C.,Liu, X. G.,Miao, Y. L.,Han, Y.,Wu, X. P.,He, G. B.,Zhong, J.,Liu, G. J. (2013). Multicenter case-control study of the risk factors for ulcerative colitis in China World J Gastroenterol, 19(11), 1827-33 | Outcome
2738 | Wang, Y. S.,Shen, Y. H.,Wang, J. J.,Yang, M. J.,Ding, S. W.,Shi, Y. Y. (1994). Preliminary study on the blood glucose level in the exclusively breastfed newborn J Trop Pediatr, 40(3), 187-8 | Intervention/exposure
2739 | Wang, Y. S.,Wu, S. Y. (1996). The effect of exclusive breastfeeding on development and incidence of infection in infants J Hum Lact, 12(1), 27-30 | Intervention/exposure
2740 | Wang, Y.,Wang, A.,Donovan, S. M.,Teran-Garcia, M. (2013). Individual genetic variations related to satiety and appetite control increase risk of obesity in preschool-age children in the STRONG kids program Hum Hered, 75(2-4), 152-9 | Study design, Intervention/exposure
2741 | Wang, Y.,Zhang, Z.,Ge, P.,Wang, Y.,Wang, S. (2009). Iodine status and thyroid function of pregnant, lactating women and infants (0-1 yr) residing in areas with an effective Universal Salt Iodization program Asia Pac J Clin Nutr, 18(1), 34-40 | Study design, Intervention/exposure
2742 | Warner, J. O. (1980). Food allergy in fully breast-fed infants Clin Allergy, 10(2), 133-6 | Study design
2743 | Warren, J. J.,Bishara, S. E. (2002). Duration of nutritive and nonnutritive sucking behaviors and their effects on the dental arches in the primary dentition Am J Orthod Dentofacial Orthop, 121(4), 347-56 | Size of study groups
2744 | Warrington, S.,Storey, D. M. (1988). Comparative studies on Asian and Caucasian children. 2: Nutrition, feeding practices and health Eur J Clin Nutr, 42(1), 69-79 | Study design, Intervention/exposure
2745 | Watase, S.,Mourino, A. P.,Tipton, G. A. (1998). An analysis of malocclusion in children with otitis media Pediatr Dent, 20(5), 327-30 | Study design
2746 | Watkinson, M. (1981). Delayed onset of weanling diarrhoea associated with high breast milk intake Trans R Soc Trop Med Hyg, 75(3), 432-5 | Country
2747 | Watson, E.,Gardner, A.,Carpenter, R. G. (1981). An epidemiological and sociological study of unexpected death in infancy in nine areas of southern England. I: Epidemiology Med Sci Law, 21(2), 78-88 | Intervention/exposure
2748 | Watson, P. E.,McDonald, B. W. (2013). Subcutaneous body fat in pregnant New Zealand women: association with wheeze in their infants at 18 months Matern Child Health J, 17(5), 959-67 | Study design
2749 | Waylen, A.,Ford, T.,Goodman, R.,Samara, M.,Wolke, D. (2009). Can early intake of dietary omega-3 predict childhood externalizing behaviour? Acta Paediatr, 98(11), 1805-8 | Outcome
2750 | Weber, F.,Woolridge, M. W.,Baum, J. D. (1986). An ultrasonographic study of the organisation of sucking and swallowing by newborn infants Dev Med Child Neurol, 28(1), 19-24 | Outcome, Size of study groups
2751 | Weber, M.,Grote, V.,Closa-Monasterolo, R.,Escribano, J.,Langhendries, J. P.,Dain, E.,Giovannini, M.,Verduci, E.,Gruszfeld, D.,Socha, P.,Koletzko, B. (2014). Lower protein content in infant formula reduces BMI and obesity risk at school age: follow-up of a randomized trial Am J Clin Nutr, 99(5), 1041-51 | Intervention/exposure
2752 | Weden, M. M.,Brownell, P.,Rendall, M. S. (2012). Prenatal, perinatal, early life, and sociodemographic factors underlying racial differences in the likelihood of high body mass index in early childhood Am J Public Health, 102(11), 2057-67 | Intervention/exposure
2753 | Weerheijm, K. L.,Uyttendaele-Speybrouck, B. F.,Euwe, H. C.,Groen, H. J. (1998). Prolonged demand breast-feeding and nursing caries Caries Res, 32(1), 46-50 | Study design
2754 | Weggemann, T.,Brown, J. K.,Fulford, G. E.,Minns, R. A. (1987). A study of normal baby movements Child Care Health Dev, 13(1), 41-58 | Size of study groups
2755 | Wegienka, G.,Ownby, D. R.,Havstad, S.,Williams, L. K.,Johnson, C. C. (2006). Breastfeeding history and childhood allergic status in a prospective birth cohort Ann Allergy Asthma Immunol, 97(1), 78-83 | Outcome
2756 | Wehby, G. L. (2014). Breastfeeding and child disability: a comparison of siblings from the United States Econ Hum Biol, 15(#issue#), 13-22 | Outcome
2757 | Weijs, P. J.,Kool, L. M.,van Baar, N. M.,van der Zee, S. C. (2011). High beverage sugar as well as high animal protein intake at infancy may increase overweight risk at 8 years: a prospective longitudinal pilot study Nutr J, 10(#issue#), 95 | Study design
2758 | Weile, B.,Cavell, B.,Nivenius, K.,Krasilnikoff, P. A. (1995). Striking differences in the incidence of childhood celiac disease between Denmark and Sweden: a plausible explanation J Pediatr Gastroenterol Nutr, 21(1), 64-8 | Study design, Intervention/exposure, Participant health
2759 | Weinstein, P.,Domoto, P.,Wohlers, K.,Koday, M. (1992). Mexican-American parents with children at risk for baby bottle tooth decay: pilot study at a migrant farmworkers clinic ASDC J Dent Child, 59(5), 376-83 | Study design
2760 | Weisgerber, M. C.,Lye, P. S.,Nugent, M.,Li, S. H.,De Fouw, K.,Gedeit, R.,Simpson, P.,Gorelick, M. H. (2013). Relationship between caloric intake and length of hospital stay for infants with bronchiolitis Hosp Pediatr, 3(1), 24-30 | Participant health
2761 | Welander, A.,Montgomery, S. M.,Ludvigsson, J.,Ludvigsson, J. F. (2014). Infectious disease at gluten introduction and risk of childhood diabetes mellitus J Pediatr, 165(2), 326-331 e1 | Outcome
2762 | Welander, A.,Tjernberg, A. R.,Montgomery, S. M.,Ludvigsson, J.,Ludvigsson, J. F. (2010). Infectious disease and risk of later celiac disease in childhood Pediatrics, 125(3), e530-6 | Outcome
2763 | Welch, K. R.,Ariza, A. J.,Wieczorek, J. L.,Binns, H. J. (2008). Characteristics of obese children aged 1-4 years at a referral clinic J Natl Med Assoc, 100(8), 884-91 | Study design
2764 | Welford H (1995). Breastfeeding: promoting good practice Mod Midwife, 5(#issue#), 29-30 | Study design
2765 | Weller, B. F. (1988). When is breast best? Nurs Stand, 3(11), 34-5 | Study design
2766 | Welliver, R. C.,Wong, D. T.,Sun, M.,McCarthy, N. (1986). Parainfluenza virus bronchiolitis. Epidemiology and pathogenesis Am J Dis Child, 140(1), 34-40 | Outcome
2767 | Wells, J. C.,Jonsdottir, O. H.,Hibberd, P. L.,Fewtrell, M. S.,Thorsdottir, I.,Eaton, S.,Lucas, A.,Gunnlaugsson, G.,Kleinman, R. E. (2012). Randomized controlled trial of 4 compared with 6 mo of exclusive breastfeeding in Iceland: differences in breast-milk intake by stable-isotope probe Am J Clin Nutr, 96(1), 73-9 | Intervention/exposure
2768 | Wells, J. C.,Stanley, M.,Laidlaw, A. S.,Day, J. M.,Davies, P. S. (1998). Energy intake in early infancy and childhood fatness Int J Obes Relat Metab Disord, 22(5), 387-92 | Size of study groups
2769 | Wen, L. M.,Baur, L. A.,Rissel, C.,Simpson, J. M. (2011). A randomized controlled trial of an early intervention on childhood obesity: Results from the first 12 months Obesity (Silver Spring, Md.), 19(#issue#), S67 | Publication status
2770 | Wen, L. M.,Baur, L. A.,Rissel, C.,Xu, H.,Simpson, J. M. (2014). Correlates of body mass index and overweight and obesity of children aged 2 years: findings from the healthy beginnings trial Obesity (Silver Spring), 22(7), 1723-30 | Outcome
2771 | Wen, L. M.,Baur, L. A.,Simpson, J. M.,Rissel, C.,Wardle, K.,Flood, V. M. (2013). Healthy beginnings trial: The journey from the beginning Obesity research & clinical practice, 7(#issue#), e2 | Publication status
2772 | Wen, X.,Kong, K. L.,Eiden, R. D.,Sharma, N. N.,Xie, C. (2014). Sociodemographic differences and infant dietary patterns Pediatrics, 134(5), e1387-98 | Intervention/exposure
2773 | Wen, X.,Shenassa, E. D.,Paradis, A. D. (2013). Maternal smoking, breastfeeding, and risk of childhood overweight: findings from a national cohort Matern Child Health J, 17(4), 746-55 | Intervention/exposure
2774 | Weng, S. F.,Redsell, S. A.,Nathan, D.,Swift, J. A.,Yang, M.,Glazebrook, C. (2013). Estimating overweight risk in childhood from predictors during infancy Pediatrics, 132(2), e414-21 | Outcome
2775 | Werneck, R. I.,Lawrence, H. P.,Kulkarni, G. V.,Locker, D. (2008). Early childhood caries and access to dental care among children of Portuguese-speaking immigrants in the city of Toronto J Can Dent Assoc, 74(9), 805 | Study design
2776 | Weston, J. (1986). Bottle feeding Nursing (Lond), 3(2), 61-2 | Study design
2777 | Wetzig, H.,Schulz, R.,Diez, U.,Herbarth, O.,Viehweg, B.,Borte, M. (2000). Associations between duration of breast-feeding, sensitization to hens’ eggs and eczema infantum in one and two year old children at high risk of atopy Int J Hyg Environ Health, 203(1), 17-21 | Intervention/exposure
2778 | Weyermann, M.,Brenner, H.,Rothenbacher, D. (2007). Adipokines in human milk and risk of overweight in early childhood: a prospective cohort study Epidemiology, 18(6), 722-9 | Outcome
2779 | Weyermann, M.,Rothenbacher, D.,Brenner, H. (2006). Duration of breastfeeding and risk of overweight in childhood: a prospective birth cohort study from Germany Int J Obes (Lond), 30(8), 1281-7 | Outcome
2780 | Wheeler, B. J.,Dickson, N. P.,Houghton, L. A.,Ward, L. M.,Taylor, B. J. (2015). Incidence and characteristics of vitamin D deficiency rickets in New Zealand children: a New Zealand Paediatric Surveillance Unit study Aust N Z J Public Health, 39(4), 380-3 | Study design, Intervention/exposure
2781 | While A (1985). Infant feeding. Breast versus bottle Nurs Mirror, 160(#issue#), 30-4 | Study design
2782 | White, C. (2000). Breast milk is still a winning formula, says study Nursing Times, 96(11), 12-12 1p | Study design
2783 | White, V. (2008). Breastfeeding and the risk of early childhood caries Evid Based Dent, 9(3), 86-8 | Study design
2784 | Whitehead, R. G. (1983). Nutritional aspects of human lactation Lancet, 1(8317), 167-9 | Study design
2785 | Whitehead, R. G. (1985). Infant physiology, nutritional requirements, and lactational adequacy Am J Clin Nutr, 41(2 Suppl), 447-58 | Study design, Intervention/exposure
2786 | Whitehead, R. G.,Paul, A. A. (1981). Infant growth and human milk requirements. A fresh approach Lancet, 2(8239), 161-3 | Size of study groups, Intervention/exposure
2787 | Whitehead, R. G.,Paul, A. A.,Ahmed, E. A. (1986). Weaning practices in the United Kingdom and variations in anthropometric development Acta Paediatr Scand Suppl, 323(#issue#), 14-23 | Size of study groups
2788 | Whitehouse, A. J.,Robinson, M.,Li, J.,Oddy, W. H. (2011). Duration of breast feeding and language ability in middle childhood Paediatr Perinat Epidemiol, 25(1), 44-52 | Outcome
2789 | Whitley, E.,Gunnell, D.,Davey Smith, G.,Holly, J. M.,Martin, R. M. (2008). Childhood circumstances and anthropometry: the Boyd Orr cohort Ann Hum Biol, 35(5), 518-34 | Study design
2790 | Whitley, E.,Martin, R. M.,Davey Smith, G.,Holly, J. M.,Gunnell, D. (2012). The association of childhood height, leg length and other measures of skeletal growth with adult cardiovascular disease: the Boyd-Orr cohort J Epidemiol Community Health, 66(1), 18-23 | Intervention/exposure
2791 | Whu, R.,Cirilo, G.,Wong, J.,Finkel, M. L.,Mendez, H. A.,Leggiadro, R. J. (2007). Risk factors for pediatric asthma in the South Bronx J Asthma, 44(10), 855-9 | Size of study groups, Intervention/exposure
2792 | Wi, C. I.,Park, M. A.,Juhn, Y. J. (2015). Development and initial testing of Asthma Predictive Index for a retrospective study: an exploratory study J Asthma, 52(2), 183-90 | Study design, Size of study groups
2793 | Wiberger, M.,Eiben, G.,Lissner, L.,Mehlig, K.,Papoutsou, S.,Hunsberger, M. (2014). Children consuming milk cereal drink are at increased risk for overweight: The IDEFICS Sweden study, on behalf of the IDEFICS Consortium Scand J Public Health, 42(6), 518-24 | Intervention/exposure
2794 | Wickens, K.,Black, P.,Stanley, T. V.,Mitchell, E.,Barthow, C.,Fitzharris, P. (2012). A protective effect of Lactobacillus rhamnosus HN001 against eczema in the first 2 years of life persists to age 4 years Clinical and Experimental Allergy, 42(7), 1071-9 | Intervention/exposure
2795 | Wickman, M.,Melen, E.,Berglind, N.,Lennart Nordvall, S.,Almqvist, C.,Kull, I.,Svartengren, M.,Pershagen, G. (2003). Strategies for preventing wheezing and asthma in small children Allergy, 58(8), 742-7 | Intervention/exposure
2796 | Wigg, N. R.,Tong, S.,McMichael, A. J.,Baghurst, P. A.,Vimpani, G.,Roberts, R. (1998). Does breastfeeding at six months predict cognitive development? Aust N Z J Public Health, 22(2), 232-6 | Outcome
2797 | Wijga, A. H.,Scholtens, S.,Bemelmans, W. J. E.,Kerkhof, M.,Koppelman, G. H.,Brunekreef, B.,Smit, H. A. (2010). Diet, screen time, physical activity, and childhood overweight in the general population and in high risk subgroups: prospective analyses in the PIAMA birth cohort Journal of Obesity, #volume#(#issue#), 9p-9p 1p | Outcome
2798 | Willatts, P.,Forsyth, S.,Agostoni, C.,Casaer, P.,Riva, E.,Boehm, G. (2013). Effects of long-chain PUFA supplementation in infant formula on cognitive function in later childhood Am J Clin Nutr, 98(2), 536S-42S | Intervention/exposure
2799 | Williams, C.,Birch, E. E.,Emmett, P. M.,Northstone, K. (2001). Stereoacuity at age 3.5 y in children born full-term is associated with prenatal and postnatal dietary factors: a report from a population-based cohort study Am J Clin Nutr, 73(2), 316-22 | Outcome
2800 | Williams, D. M.,Martin, R. M.,Davey Smith, G.,Alberti, K. G.,Ben-Shlomo, Y.,McCarthy, A. (2012). Associations of infant nutrition with insulin resistance measures in early adulthood: evidence from the Barry-Caerphilly Growth (BCG) study PLoS One, 7(3), e34161 | Intervention/exposure
2801 | Williams, S. A.,Hargreaves, J. A. (1990). An inquiry into the effects of health related behaviour on dental health among young Asian children resident in a fluoridated city in Canada Community Dent Health, 7(4), 413-20 | Study design
2802 | Williams, S. M.,Taylor, B. J.,Ford, R. P.,Nelson, E. A. (1990). Growth velocity before sudden infant death Arch Dis Child, 65(12), 1315-8 | Intervention/exposure
2803 | Williams, S. M.,Taylor, B. J.,Mitchell, E. A.,Scragg, R.,Ford, R. P.,Stewart, A. W. (1995). Sudden infant death syndrome in New Zealand: are risk scores useful? New Zealand National Cot Death Study Group J Epidemiol Community Health, 49(1), 94-101 | Outcome
2804 | Williams, S. M.,Taylor, R. W.,Taylor, B. J. (2013). Secular changes in BMI and the associations between risk factors and BMI in children born 29 years apart Pediatr Obes, 8(1), 21-30 | Intervention/exposure
2805 | Williamson, E.,Morley, R.,Lucas, A.,Carpenter, J. (2012). Propensity scores: from naive enthusiasm to intuitive understanding Stat Methods Med Res, 21(3), 273-93 | Study design, Participant health
2806 | Williamson, I. G.,Dunleavey, J.,Robinson, D. (1994). Risk factors in otitis media with effusion. A 1 year case control study in 5-7 year old children Fam Pract, 11(3), 271-4 | Study design
2807 | Willows, N. D.,Dewailly, E.,Gray-Donald, K. (2000). Anemia and iron status in Inuit infants from northern Quebec Can J Public Health, 91(6), 407-10 | Intervention/exposure
2808 | Wilson, A. C.,Forsyth, J. S.,Greene, S. A.,Irvine, L.,Hau, C.,Howie, P. W. (1998). Relation of infant diet to childhood health: seven year follow up of cohort of children in Dundee infant feeding study BMJ, 316(7124), 21-5 | Outcome
2809 | Wilson, C. E. (2000). Cree infant care practices and sudden infant death syndrome Can J Public Health, 91(2), 133-6 | Study design, Outcome
2810 | Wingard, D. L.,Criqui, M. H.,Edelstein, S. L.,Tucker, J.,Tomlinson-Keasey, C.,Schwartz, J. E.,Friedman, H. S. (1994). Is breast-feeding in infancy associated with adult longevity? Am J Public Health, 84(9), 1458-62 | Outcome
2811 | Wojcicki, J. M.,Young, M. B.,Perham-Hester, K. A.,de Schweinitz, P.,Gessner, B. D. (2015). Risk factors for obesity at age 3 in Alaskan children, including the role of beverage consumption: results from Alaska PRAMS 2005-2006 and its three-year follow-up survey, CUBS, 2008-2009 PLoS One, 10(3), e0118711 | Outcome
2812 | Wolman, P. G. (1984). Feeding practices in infancy and prevalence of obesity in preschool children J Am Diet Assoc, 84(4), 436-8 | Outcome
2813 | Wong, H. B. (1982). Child health in Singapore--past, present and future Ann Acad Med Singapore, 11(3), 322-35 | Study design
2814 | Wong, W. W.,Hachey, D. L.,Insull, W.,Opekun, A. R.,Klein, P. D. (1993). Effect of dietary cholesterol on cholesterol synthesis in breast-fed and formula-fed infants J Lipid Res, 34(8), 1403-11 | Size of study groups
2815 | Woo, J. G.,Guerrero, M. L.,Ruiz-Palacios, G. M.,Peng, Y. M.,Herbers, P. M.,Yao, W.,Ortega, H.,Davidson, B. S.,McMahon, R. J.,Morrow, A. L. (2013). Specific infant feeding practices do not consistently explain variation in anthropometry at age 1 year in urban United States, Mexico, and China cohorts J Nutr, 143(2), 166-74 | Outcome
2816 | Wood, C. S.,Isaacs, P. C.,Jensen, M.,Hilton, H. G. (1988). Exclusively breast-fed infants: growth and caloric intake Pediatr Nurs, 14(2), 117-24 | Size of study groups
2817 | Wood, R.,Stockton, D.,Brown, H. (2013). Moving from a universal to targeted child health programme: which children receive enhanced care? A population-based study using routinely available data Child Care Health Dev, 39(6), 772-81 | Outcome
2818 | Woodward, A.,Douglas, R. M.,Graham, N. M.,Miles, H. (1990). Acute respiratory illness in Adelaide children: breast feeding modifies the effect of passive smoking J Epidemiol Community Health, 44(3), 224-30 | Outcome
2819 | Worobey, J. (1993). Effects of feeding method on infant temperament Adv Child Dev Behav, 24(#issue#), 37-61 | Study design
2820 | Wray, J. (2008). Breastfeeding and primitive neonatal reflexes Pract Midwife, 11(5), 53-6 | Study design
2821 | Wright Mda, G.,Dutra de Oliveira, J. E. (1986). Is breast feeding the solution to the infant nutrition problem in underdeveloped countries? Child Care Health Dev, 12(6), 359-68 | Study design
2822 | Wright, A. L.,Bauer, M.,Naylor, A.,Sutcliffe, E.,Clark, L. (1998). Increasing breastfeeding rates to reduce infant illness at the community level Pediatrics, 101(5), 837-44 | Outcome
2823 | Wright, A. L.,Holberg, C. J.,Martinez, F. D.,Morgan, W. J.,Taussig, L. M. (1989). Breast feeding and lower respiratory tract illness in the first year of life. Group Health Medical Associates BMJ, 299(6705), 946-9 | Outcome
2824 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. (2000). Maternal asthma status alters relation of infant feeding to asthma in childhood Adv Exp Med Biol, 478(#issue#), 131-7 | Intervention/exposure
2825 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D. (1995). Relationship of infant feeding to recurrent wheezing at age 6 years Arch Pediatr Adolesc Med, 149(7), 758-63 | Outcome
2826 | Wright, A. L.,Holberg, C. J.,Taussig, L. M.,Martinez, F. D. (2001). Factors influencing the relation of infant feeding to asthma and recurrent wheeze in childhood Thorax, 56(3), 192-7 | Redundant data with another article
2827 | Wright, A. L.,Stern, D. A.,Halonen, M. (2001). The association of allergic sensitization in mother and child in breast-fed and formula-fed infants Adv Exp Med Biol, 501(#issue#), 249-55 | Outcome
2828 | Wright, C. J.,Atkinson, F. S.,Ramalingam, N.,Buyken, A. E.,Brand-Miller, J. C. (2015). Effects of human milk and formula on postprandial glycaemia and insulinaemia Eur J Clin Nutr, 69(8), 939-43 | Participant age
2829 | Wright, C. M.,Parkinson, K.,Scott, J. (2006). Breast-feeding in a UK urban context: who breast-feeds, for how long and does it matter? Public Health Nutr, 9(6), 686-91 | Outcome
2830 | Wright, C. M.,Stone, D. H.,Parkinson, K. N. (2010). Undernutrition in British Haredi infants within the Gateshead Millennium cohort study Arch Dis Child, 95(8), 630-3 | Outcome
2831 | Wright, C.,Lakshman, R.,Emmett, P.,Ong, K. K. (2008). Implications of adopting the WHO 2006 Child Growth Standard in the UK: two prospective cohort studies Arch Dis Child, 93(7), 566-9 | Intervention/exposure
2832 | Wright, P. (1981). Development of feeding behaviour in early infancy: implications for obesity Health Bull (Edinb), 39(3), 197-205 | Study design, Intervention/exposure
2833 | Wu, T. C.,Hwang, B. (1997). Blood nutrient indices in breast and formula fed infants: amino acids metabolic responses Zhonghua Min Guo Xiao Er Ke Yi Xue Hui Za Zhi, 38(5), 345-51 | Outcome
2834 | Wyne, A. H.,Adenubi, J. O.,Shalan, T.,Khan, N. (1995). Feeding and socioeconomic characteristics of nursing caries children in a Saudi population Pediatr Dent, 17(7), 451-4 | Study design
2835 | Xenellis, J.,Paschalidis, J.,Georgalas, C.,Davilis, D.,Tzagaroulakis, A.,Ferekidis, E. (2005). Factors influencing the presence of otitis media with effusion 16 months after initial diagnosis in a cohort of school-age children in rural Greece: a prospective study Int J Pediatr Otorhinolaryngol, 69(12), 1641-7 | Participant health
2836 | Xie, L. L.,Jiang, L. (2014). Arterial ischemic stroke and hemorrhagic stroke in Chinese children: a retrospective analysis Brain Dev, 36(2), 153-8 | Participant health, Outcomes
2837 | Yadav, M.,Akobeng, A. K.,Thomas, A. G. (2000). Breast-feeding and childhood obesity J Pediatr Gastroenterol Nutr, 30(3), 345-6 | Study design
2838 | Yakubov, R.,Nadir, E.,Stein, R.,Klein-Kremer, A. (2015). The Duration of Breastfeeding and Its Association with Metabolic Syndrome among Obese Children ScientificWorldJournal, 2015(#issue#), 731319 | Study design
2839 | Yalcin, S. S.,Hizli, S.,Yurdakok, K.,Ozmert, E. (2005). Risk factors for hospitalization in children with acute diarrhea: a case control study Turk J Pediatr, 47(4), 339-42 | Participant health
2840 | Yalcin, S. S.,Turul, B.,Cetinkaya, S.,Cakir, B.,Yilmaz, A. (2004). Effect of total attending period on infection episode rate in a child-care center Pediatr Int, 46(5), 555-60 | Outcome
2841 | Yamakawa, M.,Yorifuji, T.,Inoue, S.,Kato, T.,Doi, H. (2013). Breastfeeding and obesity among schoolchildren: a nationwide longitudinal survey in Japan JAMA Pediatr, 167(10), 919-25 | Intervention/exposure
2842 | Yamakawa, M.,Yorifuji, T.,Kato, T.,Inoue, S.,Tokinobu, A.,Tsuda, T.,Doi, H. (2015). Long-Term Effects of Breastfeeding on Children’s Hospitalization for Respiratory Tract Infections and Diarrhea in Early Childhood in Japan Matern Child Health J, 19(9), 1956-65 | Outcome
2843 | Yamakawa, M.,Yorifuji, T.,Kato, T.,Yamauchi, Y.,Doi, H. (2015). Breast-feeding and hospitalization for asthma in early childhood: a nationwide longitudinal survey in Japan Public Health Nutr, 18(10), 1756-61 | Intervention/exposure
2844 | Yamauchi, Y.,Yamanouchi, I. (1990). The relationship between rooming-in/not rooming-in and breast-feeding variables Acta Paediatr Scand, 79(11), 1017-22 | Intervention/exposure
2845 | Yamauchi, Y.,Yamanouchi, I. (1992). The relationship between rooming-in/not rooming-in and breastfeeding variables Breastfeeding Review, 2(5), 238-241 4p | Intervention/exposure, Duplicate
2846 | Yamborisut, U.,Kosulwat, V.,Chittchang, U.,Wimonpeerapattana, W.,Suthutvoravut, U. (2006). Factors associated with dual form of malnutrition in school children in Nakhon Pathom and Bangkok J Med Assoc Thai, 89(7), 1012-23 | Study design
2847 | Yang, S.,Fombonne, E.,Kramer, M. S. (2011). Duration of gestation, size at birth and later childhood behaviour Paediatr Perinat Epidemiol, 25(4), 377-87 | Intervention/exposure
2848 | Yang, S.,Platt, R. W.,Dahhou, M.,Kramer, M. S. (2014). Do population-based interventions widen or narrow socioeconomic inequalities? The case of breastfeeding promotion Int J Epidemiol, 43(4), 1284-92 | Outcome
2849 | Ye, M.,Mandhane, P. J.,Senthilselvan, A. (2012). Association of breastfeeding with asthma in young Aboriginal children in Canada Can Respir J, 19(6), 361-6 | Study design
2850 | Ye, W.,Feng, X. P.,Liu, Y. L. (1999). Epidemiological study of the risk factors of rampant caries in Shanghai children Chin J Dent Res, 2(2), 58-62 | Study design
2851 | Yeung, D. L.,Pennell, M. D.,Leung, M.,Hall, J. (1981). Infant fatness and feeding practices: a longitudinal assessment J Am Diet Assoc, 79(5), 531-5 | Outcome
2852 | Yeung, K. A.,Taylor, T.,Scheimann, A.,Carvalho, R.,Reinhardt, E.,Girolami, P.,Wood, R. (2015). The Prevalence of Food Allergies in Children Referred to a Multidisciplinary Feeding Program Clin Pediatr (Phila), 54(11), 1081-6 | Participant health
2853 | Yi, M. J.,Sun, D. F.,Zhou, X. B. (2003). Relationship between infant breast feeding and simple obesity in preschool children: A case-control study Chinese Journal of Clinical Rehabilitation, 7(30), 4088-4089 | Study design
2854 | Yi, M. J.,Sun, M. H.,Liu, F.,Liu, Y. (2007). Association between infant breastfeeding and temperamental characteristics development in children aged 4-5 years Journal of Clinical Rehabilitative Tissue Engineering Research, 11(30), 6100-6102 | Study design
2855 | Yildirim, Ş,Binnetoğlu, F. K.,Aylanç, H.,Battal, F.,Tekin, M.,Kaymaz, N.,Topaloğlu, N.,A§Ik, Z. (2015). Effect of infant feeding on epicardial fat thickness in normal weighted children Anatolian Journal of Clinical Investigation, 9(3), 92-97 | Study design, Participant health
2856 | Yimyaem, P.,Chongsrisawat, V.,Vivatvakin, B.,Wisedopas, N. (2003). Gastrointestinal manifestations of cow’s milk protein allergy during the first year of life J Med Assoc Thai, 86(2), 116-23 | Study design
2857 | Yin, J.,Quinn, S.,Dwyer, T.,Ponsonby, A. L.,Jones, G. (2012). Maternal diet, breastfeeding and adolescent body composition: a 16-year prospective study Eur J Clin Nutr, 66(12), 1329-34 | Outcome
2858 | Yip R,Parvanta I,Scanlon K,Borland EW,Russell CM,Trowbridge FL (1992). Pediatric nutrition surveillance system--United States, 1980-1991 MMWR CDC Surveill Summ, 41(#issue#), 1-24 | Intervention/exposure, Outcome, Publication status
2859 | Yiş, U.,Öztürk, Y.,Şişman, A. R.,Uysal, S.,Soylu Ö, B.,Büyükgebiz, B. (2010). The relation of serum ghrelin, leptin and insulin levels to the growth patterns and feeding characteristics in breast-fed versus formula-fed infants Turkish Journal of Pediatrics, 52(1), 35-41 | Size of study groups
2860 | Yoneyama, K.,Nagata, H.,Asano, H. (1994). Growth of Japanese breast-fed and bottle-fed infants from birth to 20 months Ann Hum Biol, 21(6), 597-608 | Intervention/exposure
2861 | Yonezu, T.,Ushida, N.,Yakushiji, M. (2006). Longitudinal study of prolonged breast- or bottle-feeding on dental caries in Japanese children Bull Tokyo Dent Coll, 47(4), 157-60 | Outcome
2862 | Yonezu, T.,Yotsuya, K.,Yakushiji, M. (2006). Characteristics of breast-fed children with nursing caries Bull Tokyo Dent Coll, 47(4), 161-5 | Study design, Intervention/exposure
2863 | Yoon, H. S.,Shin, Y. J.,Ki, M. (2008). Risk factors for neonatal infections in full-term babies in South Korea Yonsei Medical Journal, 49(4), 530-536 | Outcome
2864 | Yorifuji, J.,Yorifuji, T.,Tachibana, K.,Nagai, S.,Kawai, M.,Momoi, T.,Nagasaka, H.,Hatayama, H.,Nakahata, T. (2008). Craniotabes in normal newborns: the earliest sign of subclinical vitamin D deficiency J Clin Endocrinol Metab, 93(5), 1784-8 | Intervention/exposure
2865 | Yorifuji, T.,Kubo, T.,Yamakawa, M.,Kato, T.,Inoue, S.,Tokinobu, A.,Doi, H. (2014). Breastfeeding and behavioral development: a nationwide longitudinal survey in Japan J Pediatr, 164(5), 1019-1025 e3 | Outcome
2866 | Yorifuji, T.,Murata, K.,Bjerve, K. S.,Choi, A. L.,Weihe, P.,Grandjean, P. (2013). Visual evoked potentials in children prenatally exposed to methylmercury Neurotoxicology, 37(#issue#), 15-8 | Intervention/exposure
2867 | Young, H. B.,Buckley, A. E.,Hamza, B.,Mandarano, C. (1982). Milk and lactation: some social and developmental correlates among 1,000 infants Pediatrics, 69(2), 169-75 | Size of study groups, Intervention/exposure
2868 | Young, R. J.,Antonson, D. L.,Ferguson, P. W.,Murray, N. D.,Merkel, K.,Moore, T. E. (2005). Neonatal and infant feeding: effect on bone density at 4 years J Pediatr Gastroenterol Nutr, 41(1), 88-93 | Outcome
2869 | Young, S.,O’Keeffe, P. T.,Arnott, J.,Landau, L. I. (1995). Lung function, airway responsiveness, and respiratory symptoms before and after bronchiolitis Arch Dis Child, 72(1), 16-24 | Study design, Intervention/exposure, Size of study groups
2870 | Young, T. K.,Martens, P. J.,Taback, S. P.,Sellers, E. A.,Dean, H. J.,Cheang, M.,Flett, B. (2002). Type 2 diabetes mellitus in children: prenatal and early infancy risk factors among native canadians Arch Pediatr Adolesc Med, 156(7), 651-5 | Outcome
2871 | Yu, C.,Binns, C. W.,Lee, A. H. (2015). Comparison of breastfeeding rates and health outcomes for infants receiving care from hospital outpatient clinic and community health centres in China J Child Health Care, #volume#(#issue#), #Pages# | Outcome
2872 | Yu, L. X.,Tao, Y.,Qiu, R. M.,Zhou, Y.,Zhi, Q. H.,Lin, H. C. (2015). Genetic polymorphisms of the sortase A gene and social-behavioural factors associated with caries in children: a case-control study BMC Oral Health, 15(#issue#), 54 | Study design
2873 | Yuksel, H.,Sakar, A.,Dinc, G.,Yilmaz, O.,Gozmen, S.,Yorgancioglu, A.,Ozcan, C. (2007). The frequency of wheezing phenotypes and risk factors for persistence in aegean region of Turkey J Asthma, 44(2), 89-93 | Study design
2874 | Yung, J.,Yuen, J. W. M.,Ou, Y.,Loke, A. Y. (2015). Factors associated with atopy in toddlers: A case-control study International Journal of Environmental Research and Public Health, 12(3), 2501-2520 | Study design
2875 | Yurdakok, K.,Ozmert, E.,Yalcin, S. S. (1997). Physical examination of breast-fed infants Arch Pediatr Adolesc Med, 151(4), 429-30 | Study design
2876 | Zadik, Z.,Borondukov, E.,Zung, A.,Reifen, R. (2003). Adult height and weight of breast-fed and bottle-fed Israeli infants J Pediatr Gastroenterol Nutr, 37(4), 462-7 | Intervention/exposure
2877 | Zadzinska E,Sitek A,Rosset I (2016). Relationship between pre-natal factors, the perinatal environment, motor development in the first year of life and the timing of first deciduous tooth emergence Ann Hum Biol, 43(#issue#), 25-33 | Study design
2878 | Zaini, M. Z.,Lim, C. T.,Low, W. Y.,Harun, F. (2005). Factors affecting nutritional status of Malaysian primary school children Asia Pac J Public Health, 17(2), 71-80 | Study design
2879 | Zamboni, G.,Piemonte, G.,Bolner, A.,Antoniazzi, F.,Dall’Agnola, A.,Messner, H.,Gambaro, G.,Tato, L. (1993). Influence of dietary taurine on vitamin D absorption Acta Paediatrica, International Journal of Paediatrics, 82(10), 811-815 | Size of study groups
2880 | Zamora, G.,Lutter, C. K.,Pena-Rosas, J. P. (2015). Using an equity lens in the implementation of interventions to protect, promote, and support optimal breastfeeding practices J Hum Lact, 31(1), 21-5 | Study design, Outcome
2881 | Zarnani, A. H.,Modarres, Sh,Jadali, F.,Sabahi, F.,Moazzeni, S. M.,Vazirian, F. (2004). Role of rotaviruses in children with acute diarrhea in Tehran, Iran Journal of Clinical Virology, 29(3), 189-193 | Study design, Participant health
2882 | Zedan, M.,Nasef, N.,El-Bayoumy, M.,El-Assmy, M.,Attia, G.,Zedan, M.,AlWakeel, A.,Kandil, S.,Laimon, W.,Fouda, A. (2012). Does decline of lung function in wheezy infants justify the early start of controller medications? Indian J Pediatr, 79(9), 1176-80 | Country
2883 | Zell, B. L. (2011). Breastfeeding as a community health imperative Breastfeed Med, 6(#issue#), 303-4 | Study design
2884 | Zetterstrom, R. (1998). Human milk and infant development. Foreword Biol Neonate, 74(2), 80-3 | Study design
2885 | Zhang, J.,Himes, J. H.,Guo, Y.,Jiang, J.,Yang, L.,Lu, Q.,Ruan, H.,Shi, S. (2013). Birth weight, growth and feeding pattern in early infancy predict overweight/obesity status at two years of age: a birth cohort study of Chinese infants PLoS One, 8(6), e64542 | Intervention/exposure
2886 | Zhang, J.,Jiang, J.,Himes, J. H.,Zhang, J.,Liu, G.,Huang, X.,Guo, Y.,Shi, J.,Shi, S. (2012). Determinants of high weight gain and high BMI status in the first three months in urban Chinese infants Am J Hum Biol, 24(5), 633-9 | Outcome
2887 | Zhang, S.,Liu, J.,Lo, E. C.,Chu, C. H. (2013). Dental caries status of Dai preschool children in Yunnan Province, China BMC Oral Health, 13(#issue#), 68 | Study design, Intervention/exposure
2888 | Zheng, J. S.,Liu, H.,Li, J.,Chen, Y.,Wei, C.,Shen, G.,Zhu, S.,Chen, H.,Zhao, Y. M.,Huang, T.,Li, D. (2014). Exclusive breastfeeding is inversely associated with risk of childhood overweight in a large Chinese cohort J Nutr, 144(9), 1454-9 | Intervention/exposure
2889 | Zheng, W.,Suzuki, K.,Shinohara, R.,Sato, M.,Yokomichi, H.,Yamagata, Z. (2015). Maternal smoking during pregnancy and growth in infancy: a covariance structure analysis J Epidemiol, 25(1), 44-9 | Intervention/exposure
2890 | Zhong, B. L.,Ding, J.,Chen, H. H.,Li, Y.,Xu, H. M.,Tong, J.,Wang, A. Q.,Tang, G. Z.,Zhu, J. S.,Yang, D. Q.,Liu, B.,Wang, Q.,Cheng, W. F.,Yin, E.,Xu, M. J.,Zhang, T.,Hu, T. M.,Feng, X. W.,Li, H.,Dan, T. Q.,Cheng, G. M.,Zhang, J. F.,Li, H. J.,Zhu, J. H. (2013). Depressive disorders among children in the transforming China: an epidemiological survey of prevalence, correlates, and service use Depress Anxiety, 30(9), 881-92 | Study design
2891 | Zhou, S. J.,Baghurst, P.,Gibson, R. A.,Makrides, M. (2007). Home environment, not duration of breast-feeding, predicts intelligence quotient of children at four years Nutrition, 23(3), 236-41 | Outcome
2892 | Zhou, S. J.,Sullivan, T.,Gibson, R. A.,Lonnerdal, B.,Prosser, C. G.,Lowry, D. J.,Makrides, M. (2014). Nutritional adequacy of goat milk infant formulas for term infants: a double-blind randomised controlled trial Br J Nutr, 111(9), 1641-51 | Intervention/exposure
2893 | Zhou, S. J.,Sullivan, T.,Gibson, R. A.,Makrides, M. (2011). How does goat milk infant formula compare to cow milk formula? A randomised controlled trial [conference abstract] Journal of pediatric gastroenterology and nutrition, 52(#issue#), E208-e209 | Publication status
2894 | Ziajka, S.,Zbikowski, Z. (1986). Characterization and properties of infant milk formulae with addition of enzymatically digested casein Nahrung, 30(3-4), 413-4 | Study design, Intervention/exposure
2895 | Ziegler, A. G.,Schmid, S.,Huber, D.,Hummel, M.,Bonifacio, E. (2003). Early infant feeding and risk of developing type 1 diabetes-associated autoantibodies JAMA, 290(13), 1721-8 | Outcome
2896 | Ziegler, E. E.,Fields, D. A.,Chernausek, S. D.,Steenhout, P.,Grathwohl, D.,Jeter, J. M.,Nelson, S. E.,Haschke, F. (2015). Adequacy of Infant Formula With Protein Content of 1.6 g/100 kcal for Infants Between 3 and 12 Months J Pediatr Gastroenterol Nutr, 61(5), 596-603 | Intervention/exposure
2897 | Ziegler, E. E.,Hollis, B. W.,Nelson, S. E.,Jeter, J. M. (2006). Vitamin D deficiency in breastfed infants in Iowa Pediatrics, 118(2), 603-10 | Intervention/exposure
2898 | Ziegler, E. E.,Jiang, T.,Romero, E.,Vinco, A.,Frantz, J. A.,Nelson, S. E. (1999). Cow’s milk and intestinal blood loss in late infancy J Pediatr, 135(6), 720-6 | Intervention/exposure, Outcome
2899 | Ziegler, E. E.,Nelson, S. E.,Jeter, J. M. (2014). Iron stores of breastfed infants during the first year of life Nutrients, 6(5), 2023-34 | Intervention/exposure
2900 | Ziegler, E.,Vanderhoof, J. A.,Petschow, B.,Mitmesser, S. H.,Stolz, S. I.,Harris, C. L.,Berseth, C. L. (2007). Term infants fed formula supplemented with selected blends of prebiotics grow normally and have soft stools similar to those reported for breast-fed infants J Pediatr Gastroenterol Nutr, 44(3), 359-64 | Intervention/exposure
2901 | Zielhuis, G. A.,Heuvelmans-Heinen, E. W.,Rach, G. H.,van den Broek, P. (1989). Environmental risk factors for otitis media with effusion in preschool children Scand J Prim Health Care, 7(1), 33-8 | Outcome
2902 | Zive, M. M.,McKay, H.,Frank-Spohrer, G. C.,Broyles, S. L.,Nelson, J. A.,Nader, P. R. (1992). Infant-feeding practices and adiposity in 4-y-old Anglo- and Mexican-Americans Am J Clin Nutr, 55(6), 1104-8 | Study design
2903 | Zollner, M. S.,Jorge, A. O. (2003). Candida spp. occurrence in oral cavities of breastfeeding infants and in their mothers’ mouths and breasts Pesqui Odontol Bras, 17(2), 151-5 | Study design
2904 | Zoppi, G.,Ferrarini, G.,Rigolin, F.,Bogaerts, H.,Andre, F. E. (1986). Response to RIT 4237 oral rotavirus vaccine in breast-fed and formula-fed infants Helv Paediatr Acta, 41(3), 203-8 | Size of study groups
2905 | Zoppi, G.,Mantovanelli, F.,Gobio Casali, L.,Astolfi, R.,Cecchettin, M. (1986). Effects of the composition and caloric value of infant formulas on intake and hormone levels J Pediatr Gastroenterol Nutr, 5(5), 756-61 | Size of study groups
2906 | Zuccotti, G.,Vigano, A.,Cafarelli, L.,Pivetti, V.,Pogliani, L.,Puzzovio, M.,Mora, S. (2011). Longitudinal changes of bone ultrasound measurements in healthy infants during the first year of life: influence of gender and type of feeding Calcif Tissue Int, 89(4), 312-7 | Size of study groups, Outcome
2907 | (1980). Nutritional adequacy of breast feeding Nutr Rev, 38(#issue#), 145-7 | Publication status
2908 | (1983). Breast-feeding and human milk Eur J Obstet Gynecol Reprod Biol, 15(4-6), 385-94 | Publication status
2909 | (1984). Bioavailability of milk zinc in infants Nutr Rev, 42(#issue#), 220-2 | Publication status
2910 | (1984). Project report. Results and policy implications of the cross-national investigation: Rethinking Infant Nutrition Policies under changing Socio-Economic Conditions Acta Paediatr Scand Suppl, 314(#issue#), 1-61 | Publication status
2911 | (1985). Breast feeding and child development at five years Nutr Rev, 43(#issue#), 173-4 | Publication status
2912 | (1985). Current issues in feeding the normal infant Pediatrics, 75(1 Pt 2), 135-215 | Publication status
2913 | (1986). Allergy in your baby Aust Fam Physician, 15(2), 176, 178 | Publication status
2914 | (1986). Catch-up growth following severe malnutrition Nutr Rev, 44(5), 173-5 | Publication status
2915 | (1986). Significance of food hypersensitivity in children with atopic dermatitis Pediatr Dermatol, 3(2), 161-74 | Publication status
2916 | (1988). Breast versus bottle: an in-house debate Midwife Health Visit Community Nurse, 24(7), 254-5 | Publication status
2917 | (1988). Cow’s milk allergy in the first year of life. An Italian Collaborative Study Acta Paediatr Scand Suppl, 348(#issue#), 1-14 | Publication status
2918 | (1988). Progress toward the 1990 objectives for improved nutrition MMWR Morb Mortal Wkly Rep, 37(#issue#), 475-9 | Publication status
2919 | (1989). American Academy of Pediatrics Committee on Nutrition: Follow-up or weaning formulas Pediatrics, 83(6), 1067 | Publication status
2920 | (1990). Nutrition for mother and child Nurs J India, 81(6), 181-8 | Publication status
2921 | (1991). Immunology of milk and the neonate Adv Exp Med Biol, 310(#issue#), 1-480 | Publication status
2922 | (1993). Diarrhoeal disease control (CDD) and acute respiratory infections (ARI). Combined CDD/ARI/breast-feeding survey, 1992 Wkly Epidemiol Rec, 68(17), 120-2 | Publication status
2923 | (1993). Diarrhoeal Disease Control (CDD) Programme Wkly Epidemiol Rec, 68(#issue#), 345-9 | Publication status
2924 | (1994). Dietary and other risk factors of ulcerative colitis. A case-control study in Japan. Epidemiology Group of the Research Committee of Inflammatory Bowel Disease in Japan J Clin Gastroenterol, 19(2), 166-71 | Intervention/exposure
2925 | (1994). Infant feeding practices and their possible relationship to the etiology of diabetes mellitus. American Academy of Pediatrics Work Group on Cow’s Milk Protein and Diabetes Mellitus Pediatrics, 94(5), 752-4 | Publication status
2926 | (1997). Breast feeding: benefits and hazards Early Hum Dev, 49 Suppl(#issue#), S1-203 | Publication status
2927 | (1998). The Baby-Friendly Hospital Initiative Birth Gaz, 14(#issue#), 30 | Publication status
2928 | (1999). Breast feeding seems to reduce the risk of obesity in children Bmj, 319(7203), B | Publication status
2929 | (1999). Exclusive breast feeding is protective against asthma and atopy in children Bmj, 319(7213), D | Publication status
2930 | (1999). Protective effect of breast milk against pneumonia is greatest for young infants Bmj, 318(7194), C | Publication status
2931 | (1999). Sudden infant death syndrome (SIDS). Canadian Foundation for the Study of Infant Deaths. Canadian Institute of Child Health. Canadian Paediatric Society Can Fam Physician, 45(#issue#), 702, 709-10 | Publication status
2932 | (1999). Vitamin D supplement in early childhood and risk for Type I (insulin-dependent) diabetes mellitus. The EURODIAB Substudy 2 Study Group Diabetologia, 42(1), 51-4 | Intervention/exposure
2933 | (2000). Growth patterns of breastfed infants in seven countries Acta Paediatr, 89(2), 215-22 | Publication status
2934 | (2001). Breastfeeding and childhood cancer Br J Cancer, 85(11), 1685-94 | Outcome
2935 | (2001). Controversial breastfeeding study Practising Midwife, 4(5), 6-6 1p | Publication status
2936 | (2001). RC currents. Children breast-fed by asthmatic mothers at risk, says study AARC Times, 25(4), 70-70 1p | Publication status
2937 | (2002). Rapid early growth is associated with increased risk of childhood type 1 diabetes in various European populations Diabetes Care, 25(10), 1755-60 | Outcome
2938 | (2004). Does breastfeeding prevent obesity?…and what about dairy foods? Child Health Alert, 22(#issue#), 3-4 | Publication status
2939 | (2004). Further evidence that breast is best RCM Midwives, #volume#(#issue#), 2-2 1p | Publication status
2940 | (2006). Study hints at link between breastfeeding and intelligence AHRQ Research Activities, #volume#(308), 10-10 1p | Publication status
2941 | (2008). Effects of breast-feeding: new results from a large randomised trial Journal of Family Health Care, 18(1), 34-34 1p | Publication status
2942 | (2008). POEMs. Breastfeeding does not decrease risk of asthma and allergy JAAPA: Journal of the American Academy of Physician Assistants (Haymarket Media, Inc.), 21(1), 66-66 1p | Publication status
2943 | (2009). Prolonged breast feeding reduces later cardiovascular risk Arch Dis Child, 94(11), 882 | Publication status
2944 | (2009). Promoting breast-feeding: fewer infections than in bottle-fed babies. Very few contraindications to breast-feeding Prescrire international, 18(102), 178 | Publication status
2945 | (2011). ABM Clinical Protocol #24: Allergic Proctocolitis in the Exclusively Breastfed Infant Breastfeed Med, 6(6), 435-40 | Publication status
2946 | (2011). Breastfeeding for the health of baby and mother Nurs J India, 102(8), 179 | Publication status
2947 | (2012). Breastfeeding study looks at behaviour Midwives, 15(1), 9-9 1p | Publication status
2948 | (2012). UP11 The Feeding Young Children Study: Preliminary Results from a WIC-based Bottle Weaning Intervention Journal of Nutrition Education & Behavior, 44(4S1), S83-S83 1p | Publication status
2949 | (2013). Does breastfeeding increase risk of early childhood caries? J Can Dent Assoc, 79(#issue#), d123 | Publication status
2950 | (2013). Start smart: healthy weight in early childhood Issue Brief (Grantmakers Health), #volume#(#issue#), 1-14 | Publication status
2951 | (2015). Breastfeeding could be linked to higher IQ Perspect Public Health, 135(3), 114 | Publication status
2952 | (2015). Breastfeeding Nurs Womens Health, 19(1), 83-8 | Publication status
2953 | (2015). Breastfeeding: sensitive mothers and intelligent offspring Arch Dis Child, 100(6), 601 | Publication status
2954 | (2015). Immediate Post-Partum Initiation of Etonogestrel-Releasing Implant: A Randomized Controlled Trial on Breastfeeding Impact #journal#, 70(#issue#), 702-704 3p | Publication status
2955 | (2015). Study Looks at Breastfeeding Impact on Leukemia Neonatal Intensive Care, 28(4), 12-14 3p | Publication status
2956 | (2015). The Optimal Duration of Exclusive Breastfeeding for Physical Growth Nutritional Perspectives: Journal of the Council on Nutrition, 38(4), 21-33 11p | Publication status

Table 23 Full-text exclusions, Update to the Pregnancy and Birth to 24 Months Project literature search

The table below lists the articles excluded after full-text screening of the update to the Pregnancy and Birth to 24 Months Project literature search. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

| Full texts screened | Reason for exclusion
1 | Abrahamse-Berkeveld, M.,Alles, M.,Franke-Beckmann, E.,Helm, K.,Knecht, R.,Kollges, R.,Sandner, B.,Knol, J.,Ben Amor, K.,Bufe, A. (2016). Infant formula containing galacto-and fructo-oligosaccharides and Bifidobacterium breve M-16V supports adequate growth and tolerance in healthy infants in a randomised, controlled, double-blind, prospective, multicentre study J Nutr Sci, 5(#issue#), e42 | Intervention/exposure vs comparator
2 | Abrams, E. M.,Greenhawt, M.,Fleischer, D. M.,Chan, E. S. (2017). Early Solid Food Introduction: Role in Food Allergy Prevention and Implications for Breastfeeding J Pediatr, 184(#issue#), 13-18 | Publication status, Study design
3 | Adeyeye, T. E.,Yeung, E. H.,McLain, A. C.,Lin, S.,Lawrence, D. A.,Bell, E. M. (2019). Wheeze and Food Allergies in Children Born via Cesarean Delivery American Journal of Epidemiology, 188(2), 355-362 | Outcome
4 | Adeyeye, T. E.,Yeung, E. H.,McLain, A. C.,Lin, S.,Lawrence, D. A.,Bell, E. M. (2019). Wheeze and Food Allergies in Children Born via Cesarean Delivery: The Upstate KIDS Study Am J Epidemiol, 188(2), 355-362 | Intervention/exposure vs comparator
5 | Aghajafari, F.,Field, C. J.,Weinberg, A. R.,Letourneau, N. (2018). Both Mother and Infant Require a Vitamin D Supplement to Ensure That Infants’ Vitamin D Status Meets Current Guidelines Nutrients, 10(4), #Pages# | Intervention/exposure vs comparator
6 | Ahrens, B.,Hellmuth, C.,Haiden, N.,Olbertz, D.,Hamelmann, E.,Vusurovic, M.,Fleddermann, M.,Roehle, R.,Knoll, A.,Koletzko, B.,Wahn, U.,Beyer, K. (2018). Hydrolyzed Formula With Reduced Protein Content Supports Adequate Growth: A Randomized Controlled Noninferiority Trial J Pediatr Gastroenterol Nutr, 66(5), 822-830 | Intervention/exposure vs comparator
7 | Akkermans, M. D.,Eussen, S. R.,van der Horst-Graat, J. M.,van Elburg, R. M.,van Goudoever, J. B.,Brus, F. (2017). A micronutrient-fortified young-child formula improves the iron and vitamin D status of healthy young European children: a randomized, double-blind controlled trial Am J Clin Nutr, 105(2), 391-399 | Intervention/exposure vs comparator
8 | Alamian, A.,Wang, L.,Hall, A. M.,Pitts, M.,Ikekwere, J. (2016). Infant sleep problems and childhood overweight: Effects of three definitions of sleep problems Prev Med Rep, 4(#issue#), 463-8 | Outcome
9 | Albaum, J. M.,Carsley, S.,Chen, Y.,Dai, D. W. H.,Lebovic, G.,McCrindle, B. W.,Maguire, J. L.,Parkin, P. C.,Birken, C. S. (2017). Persistent High Non-High-Density Lipoprotein Cholesterol in Early Childhood: A Latent Class Growth Model Analysis J Pediatr, 191(#issue#), 152-157 | Outcome
10 | Alexander, D. D.,Yan, J.,Bylsma, L. C.,Northington, R. S.,Grathwohl, D.,Steenhout, P.,Erdmann, P.,Spivey-Krobath, E.,Haschke, F. (2016). Growth of infants consuming whey-predominant term infant formulas with a protein content of 1.8 g/100 kcal: a multicenter pooled analysis of individual participant data Am J Clin Nutr, 104(4), 1083-1092 | Study design, Intervention/exposure vs comparator
11 | Al-Mesad, Y.,Davidsson, L. (2018). Assessment of body composition of kuwaiti infants by using air displacement plethysmography (PEA POD®) Irish journal of medical science, 187(#issue#), S341- | Publication status
12 | Altobelli, E.,Petrocelli, R.,Verrotti, A.,Chiarelli, F.,Marziliano, C. (2016). Genetic and environmental factors affect the onset of type 1 diabetes mellitus Pediatr Diabetes, 17(8), 559-566 | Study design, Intervention/exposure vs comparator
13 | Amaro-Rivera, K.,Molina, J.,Perez, C. M.,Palacios, C. (2019). Longitudinal Associations between Dietary Patterns and Weight Status in Puerto Rican Infants and Toddlers’ Participants of the WIC Program P R Health Sci J, 38(2), 75-80 | Intervention/exposure vs comparator
14 | Ames, J.,Warner, M.,Siracusa, C.,Signorini, S.,Brambilla, P.,Mocarelli, P.,Eskenazi, B. (2019). Prenatal dioxin exposure and neuropsychological functioning in the Seveso Second Generation Health Study Int J Hyg Environ Health, 222(3), 425-433 | Study design
15 | Amoros, R.,Murcia, M.,Gonzalez, L.,Rebagliato, M.,Iniguez, C.,Lopez-Espinosa, M. J.,Vioque, J.,Broberg, K.,Ballester, F.,Llop, S. (2018). Maternal selenium status and neuropsychological development in Spanish preschool children Environ Res, 166(#issue#), 215-222 | Intervention/exposure vs comparator
16 | Andersen, A. T. N.,Husby, S.,Sander, S. D.,Kyhl, H. B.,Sandberg, M. B.,Molgaard, C. (2016). Iron deficiency in healthy 18-month-old danish children: prevalence and associated factors: a subproject in the odense child cohort Journal of pediatric gastroenterology and nutrition, 63(#issue#), S258-S259 | Publication status
17 | Andersen, K. R.,Harslof, L. B.,Schnurr, T. M.,Hansen, T.,Hellgren, L. I.,Michaelsen, K. F.,Lauritzen, L. (2017). A study of associations between early DHA status and fatty acid desaturase (FADS) SNP and developmental outcomes in children of obese mothers Br J Nutr, 117(2), 278-286 | Study design
18 | Anderson, P. O. (2019). When the Heart Is Not in It: Breastfeeding with Cardiovascular Disease Breastfeed Med, 14(2), 80-82 | Study design
19 | Andres, Aline (2017). CHILDREN’S NUTRITION CENTER FOCUSED ON SOY FORMULA Soy Connection, 25(3), 6-7 | Publication status
20 | Anusha, K.,Hettiaratchi, U.,Gunasekera, D.,Prathapan, S.,Liyanage, G. (2019). Maternal Vitamin D Status and Its Effect on Vitamin D Levels in Early Infancy in a Tertiary Care Centre in Sri Lanka Int J Endocrinol, 2019(#issue#), 9017951 | Intervention/exposure vs comparator
21 | Ardıç, C.,Omar, E. (2019). Obesity frequency and related risk factors in primary school children European Research Journal, 5(3), 467-472 | Study design
22 | Ardic, C.,Usta, O.,Omar, E.,Yildiz, C.,Memis, E. (2019). Effects of infant feeding practices and maternal characteristics on early childhood obesity Arch Argent Pediatr, 117(1), 26-33 | Intervention/exposure vs comparator
23 | Aris, I. M.,Bernard, J. Y.,Chen, L. W.,Tint, M. T.,Pang, W. W.,Lim, W. Y.,Soh, S. E.,Saw, S. M.,Godfrey, K. M.,Gluckman, P. D.,Chong, Y. S.,Yap, F.,Kramer, M. S.,Lee, Y. S. (2017). Infant body mass index peak and early childhood cardio-metabolic risk markers in a multi-ethnic Asian birth cohort Int J Epidemiol, 46(2), 513-525 | Outcome
24 | Aris, I. M.,Bernard, J. Y.,Chen, L. W.,Tint, M. T.,Pang, W. W.,Soh, S. E.,Saw, S. M.,Shek, L. P.,Godfrey, K. M.,Gluckman, P. D.,Chong, Y. S.,Yap, F.,Kramer, M. S.,Lee, Y. S. (2018). Modifiable risk factors in the first 1000 days for subsequent risk of childhood overweight in an Asian cohort: significance of parental overweight status Int J Obes (Lond), 42(1), 44-51 | Intervention/exposure vs comparator
25 | Aris, I. M.,Rifas-Shiman, S. L.,Li, L. J.,Kleinman, K.,Coull, B. A.,Gold, D. R.,Hivert, M. F.,Kramer, M. S.,Oken, E. (2018). Pre-, Perinatal, and Parental Predictors of Body Mass Index Trajectory Milestones J Pediatr, 201(#issue#), 69-77.e8 | Outcome
26 | Aris, I. M.,Soh, S. E.,Tint, M. T.,Saw, S. M.,Rajadurai, V. S.,Godfrey, K. M.,Gluckman, P. D.,Yap, F.,Chong, Y. S.,Lee, Y. S. (2017). Associations of infant milk feed type on early postnatal growth of offspring exposed and unexposed to gestational diabetes in utero Eur J Nutr, 56(1), 55-64 | Already included in P/B24 search
27 | Ayonrinde, O. T.,Oddy, W. H.,Adams, L. A.,Mori, T. A.,Beilin, L. J.,de Klerk, N.,Olynyk, J. K. (2017). Infant nutrition and maternal obesity influence the risk of non-alcoholic fatty liver disease in adolescents J Hepatol, 67(3), 568-576 | Outcome
28 | Azad, M. B.,Vehling, L.,Chan, D.,Klopp, A.,Nickel, N. C.,McGavock, J. M.,Becker, A. B.,Mandhane, P. J.,Turvey, S. E.,Moraes, T. J.,Taylor, M. S.,Lefebvre, D. L.,Sears, M. R.,Subbarao, P. (2018). Infant Feeding and Weight Gain: Separating Breast Milk From Breastfeeding and Formula From Food Pediatrics, 142(4), #Pages# | Outcome
29 | Baïz, N.,Macchiaverni, P.,Tulic, M. K.,Rekima, A.,Annesi-Maesano, I.,Verhasselt, V.,Bernard, J. Y.,Botton, J.,Charles, M. A.,Dargent-Molina, P.,de Lauzon-Guillain, B.,Ducimetière, P.,de Agostini, M.,Foliguet, B.,Forhan, A.,Fritel, X.,Germa, A.,Goua, V.,Hankard, R.,Heude, B.,Kaminski, M.,Larroque, B.,Lelong, N.,Lepeule, J.,Magnin, G.,Pierre, F.,Marchand, L.,Nabet, C.,Slama, R.,Saurel-Cubizolles, M. J.,Schweitzer, M.,Thiebaugeorges, O. (2017). Early oral exposure to house dust mite allergen through breast milk: A potential risk factor for allergic sensitization and respiratory allergies in children Journal of Allergy and Clinical Immunology, 139(1), 369-372.e10 | Publication status
30 | Baran, J.,Weres, A.,Czenczek-Lewandowska, E.,Luszczki, E.,Sobek, G.,Pitucha, G.,Leszczak, J.,Mazur, A. (2019). Early Eating Patterns and Overweight and Obesity in a Sample of Preschool Children in South-East Poland Int J Environ Res Public Health, 16(17), #Pages# | Confounders, Intervention/exposure vs comparator
31 | Barrera, C. M.,Perrine, C. G.,Li, R.,Scanlon, K. S. (2016). Age at Introduction to Solid Foods and Child Obesity at 6 Years Child Obes, 12(3), 188-92 | Intervention/exposure vs comparator
32 | Barros, V. O.,Amorim, M. R.,Melo, A. O.,Tavares, J. S.,Silva, A. C.,Alves, J. G. (2016). Abdominal Fat Distribution Among Breastfed and Formula-Fed Infants Breastfeed Med, 11(#issue#), 231-4 | Outcome
33 | Béghin, L.,Marchandise, X.,Lien, E.,Bricout, M.,Bernet, J. P.,Lienhardt, J. F.,Jeannerot, F.,Menet, V.,Requillart, J. C.,Marx, J.,De Groot, N.,Jaeger, J.,Steenhout, P.,Turck, D. (2019). Growth, stool consistency and bone mineral content in healthy term infants fed sn-2-palmitate-enriched starter infant formula: A randomized, double-blind, multicentre clinical trial Clinical Nutrition, 38(3), 1023-1030 | Intervention/exposure vs comparator
34 | Bekhet, O. H.,Vekic, J.,Zeljkovic, A.,Paripovic, D.,Gojkovic, T.,Janac, J.,Spasojevic-Kalimanovska, V.,Peco-Antic, A.,Milosevski-Lomic, G.,Jelic-Ivanovic, Z.,Stefanovic, A. (2017). Associations of Apgar score and size at birth with lipoprotein subclasses in juvenile obesity Turk J Med Sci, 47(6), 1804-1812 | Study design
35 | Belfort, M. B.,Rifas-Shiman, S. L.,Kleinman, K. P.,Bellinger, D. C.,Harris, M. H.,Taveras, E. M.,Gillman, M. W.,Oken, E. (2016). Infant Breastfeeding Duration and Mid-Childhood Executive Function, Behavior, and Social-Emotional Development J Dev Behav Pediatr, 37(1), 43-52 | Outcome
36 | Bell, K. A.,Wagner, C. L.,Feldman, H. A.,Shypailo, R. J.,Belfort, M. B. (2017). Associations of infant feeding with trajectories of body composition and growth Am J Clin Nutr, 106(2), 491-498 | Outcome
37 | Bell, S.,Yew, S. S. Y.,Devenish, G.,Ha, D.,Do, L.,Scott, J. (2018). Duration of Breastfeeding, but Not Timing of Solid Food, Reduces the Risk of Overweight and Obesity in Children Aged 24 to 36 Months: Findings from an Australian Cohort Study Int J Environ Res Public Health, 15(4), #Pages# | Intervention/exposure vs comparator
38 | Berger, P. K.,Lavner, J. A.,Smith, J. J.,Birch, L. L. (2017). Differences in early risk factors for obesity between African American formula-fed infants and White breastfed controls Pilot Feasibility Stud, 3(#issue#), 58 | Intervention/exposure vs comparator
39 | Berghuis, S. A.,Van Braeckel, Knja,Sauer, P. J. J.,Bos, A. F. (2018). Prenatal exposure to persistent organic pollutants and cognition and motor performance in adolescence Environ Int, 121(Pt 1), 13-22 | Intervention/exposure vs comparator
40 | Bernard, J. Y.,Armand, M.,Peyre, H.,Garcia, C.,Forhan, A.,De Agostini, M.,Charles, M. A.,Heude, B. (2017). Breastfeeding, Polyunsaturated Fatty Acid Levels in Colostrum and Child Intelligence Quotient at Age 5-6 Years J Pediatr, 183(#issue#), 43-50.e3 | Outcome
41 | Besharat Pour, M.,Bergstrom, A.,Bottai, M.,Magnusson, J.,Kull, I.,Moradi, T. (2017). Age at adiposity rebound and body mass index trajectory from early childhood to adolescence; differences by breastfeeding and maternal immigration background Pediatr Obes, 12(1), 75-84 | Intervention/exposure vs comparator
42 | Betoko, A.,Lioret, S.,Heude, B.,Hankard, R.,Carles, S.,Forhan, A.,Regnault, N.,Botton, J.,Charles, M. A.,de Lauzon-Guillain, B. (2017). Influence of infant feeding patterns over the first year of life on growth from birth to 5 years Pediatr Obes, 12 Suppl 1(#issue#), 94-101 | Outcome
43 | Bider-Canfield, Z.,Martinez, M. P.,Wang, X.,Yu, W.,Bautista, M. P.,Brookey, J.,Page, K. A.,Buchanan, T. A.,Xiang, A. H. (2017). Maternal obesity, gestational diabetes, breastfeeding and childhood overweight at age 2 years Pediatr Obes, 12(2), 171-178 | Outcome
44 | Bion, V.,Lockett, G. A.,Soto-Ramirez, N.,Zhang, H.,Venter, C.,Karmaus, W.,Holloway, J. W.,Arshad, S. H. (2016). Evaluating the efficacy of breastfeeding guidelines on long-term outcomes for allergic disease Allergy, 71(5), 661-70 | Outcome
45 | Bjarnadottir, E.,Stokholm, J.,Chawes, B.,Thorsen, J.,Mora-Jensen, A. C.,Deleuran, M.,Bonnelykke, K.,Lauritzen, L.,Bisgaard, H. (2019). Determinants of neurodevelopment in early childhood - results from the Copenhagen prospective studies on asthma in childhood (COPSAC2010) mother-child cohort Acta Paediatr, 108(9), 1632-1641 | Intervention/exposure vs comparator
46 | Bjarnadóttir, E.,Stokholm, J.,Chawes, B.,Thorsen, J.,Mora-Jensen, A. R. C.,Deleuran, M.,Bønnelykke, K.,Lauritzen, L.,Bisgaard, H. (2019). Determinants of neurodevelopment in early childhood – results from the Copenhagen prospective studies on asthma in childhood (COPSAC2010) mother–child cohort Acta Paediatrica, International Journal of Paediatrics, 108(9), 1632-1641 | Duplicate
47 | Bjerregaard, L. G.,Pedersen, D. C.,Mortensen, E. L.,Sorensen, T. I. A.,Baker, J. L. (2019). Breastfeeding duration in infancy and adult risks of type 2 diabetes in a high-income country Matern Child Nutr, #volume#(#issue#), e12869 | Intervention/exposure vs comparator
48 | Bjertnaes, A. A.,Grundt, J. H.,Donkor, H. M.,Juliusson, P. B.,Wentzel-Larsen, T.,Vaktskjold, A.,Markestad, T.,Holten-Andersen, M. N. (2019). No significant associations between breastfeeding practices and overweight in 8-year-old children Acta Paediatr, #volume#(#issue#), #Pages# | Outcome
49 | Bonato, M.,Bazzan, E.,Snijders, D.,Tine, M.,Biondini, D.,Turato, G.,Balestro, E.,Papi, A.,Cosio, M. G.,Barbato, A.,Baraldo, S.,Saetta, M. (2018). Clinical and Pathologic Factors Predicting Future Asthma in Wheezing Children. A Longitudinal Study Am J Respir Cell Mol Biol, 59(4), 458-466 | Outcome
50 | Bornhorst, C.,Siani, A.,Russo, P.,Kourides, Y.,Sion, I.,Molnar, D.,Moreno, L. A.,Rodriguez, G.,Ben-Shlomo, Y.,Howe, L.,Lissner, L.,Mehlig, K.,Regber, S.,Bammann, K.,Foraita, R.,Ahrens, W.,Tilling, K. (2016). Early Life Factors and Inter-Country Heterogeneity in BMI Growth Trajectories of European Children: The IDEFICS Study PLoS One, 11(2), e0149268 | Outcome
51 | Boskabadi, H.,Akhondian, J.,Afarideh, M.,Maamouri, G.,Bagheri, S.,Parizadeh, S. M.,Mobarhan, M. G.,Mohammadi, S.,Frens, G. A. (2017). Long-Term Neurodevelopmental Outcome of Neonates with Hypernatremic Dehydration Breastfeed Med, 12(#issue#), 163-168 | Study design, Participant health
52 | Boucher, O.,Julvez, J.,Guxens, M.,Arranz, E.,Ibarluzea, J.,Sanchez de Miguel, M.,Fernandez-Somoano, A.,Tardon, A.,Rebagliato, M.,Garcia-Esteban, R.,O’Connor, G.,Ballester, F.,Sunyer, J. (2017). Association between breastfeeding duration and cognitive development, autistic traits and ADHD symptoms: a multicenter study in Spain Pediatr Res, 81(3), 434-442 | Outcome
53 | Boucher, Olivier,Julvez, Jordi,Guxens, Mònica,Arranz, Enrique,Ibarluzea, Jesús,Sánchez de Miguel, Manuel,Fernández-Somoano, Ana,Tardon, Adonina,Rebagliato, Marisa,Garcia-Esteban, Raquel,O’Connor, Giselle,Ballester, Ferran,Sunyer, Jordi (2016). Association between breastfeeding duration and cognitive development, autistic traits and ADHD symptoms: a multicenter study in Spain Pediatric Research, #volume#(#issue#), N.PAG-N.PAG | Duplicate
54 | Boutwell, B. B.,Young, J. T. N.,Meldrum, R. C. (2018). On the positive relationship between breastfeeding & intelligence Dev Psychol, 54(8), 1426-1433 | Outcome
55 | Bove, M. I.,Zelmonovich, C.,Bia, D.,Iturralde, A.,Ghiachetto, G.,Klaps, L.,Guillermo, V. (2017). Modifiable risk factors present from conception to age 2 years and their association with obesity at 5 years old Annals of nutrition & metabolism, 71(#issue#), 622-623 | Publication status
56 | Boyle, R. J.,Tang, M. L.,Chiang, W. C.,Chua, M. C.,Ismail, I.,Nauta, A.,Hourihane, J. O. B.,Smith, P.,Gold, M.,Ziegler, J.,Peake, J.,Quinn, P.,Rao, R.,Brown, N.,Rijnierse, A.,Garssen, J.,Warner, J. O. (2016). Prebiotic-supplemented partially hydrolysed cow’s milk formula for the prevention of eczema in high-risk infants: a randomized controlled trial Allergy, 71(5), 701-10 | Intervention/exposure vs comparator
57 | Brambilla, P.,Bedogni, G.,Pietrobelli, A.,Cianfarani, S.,Agostoni, C. (2016). Predictors of blood pressure at 7-13 years: The “new millennium baby” study Nutr Metab Cardiovasc Dis, 26(8), 706-12 | Outcome
58 | Breij, L. M.,Abrahamse-Berkeveld, M.,Acton, D.,De Lucia Rolfe, E.,Ong, K. K.,Hokken-Koelega, A. C. S. (2017). Impact of Early Infant Growth, Duration of Breastfeeding and Maternal Factors on Total Body Fat Mass and Visceral Fat at 3 and 6 Months of Age Ann Nutr Metab, 71(3-4), 203-210 | Outcome
59 | Breij, L. M.,Mulder, M. T.,van Vark-van der Zee, L. C.,Hokken-Koelega, A. C. S. (2017). Appetite-regulating hormones in early life and relationships with type of feeding and body composition in healthy term infants Eur J Nutr, 56(4), 1725-1732 | ConfoundersStudy design, Intervention/exposure vs comparator
60 | Bridgman, S. L.,Azad, M. B.,Persaud, R. R.,Chari, R. S.,Becker, A. B.,Sears, M. R.,Mandhane, P. J.,Turvey, S. E.,Subbarao, P.,Haqq, A. M.,Kozyrskyj, A. L. (2018). Impact of maternal pre-pregnancy overweight on infant overweight at 1 year of age: associations and sex-specific differences Pediatr Obes, 13(10), 579-589 | Intervention/exposure vs comparator
61 | Brouwer-Brolsma, E. M.,van de Rest, O.,Godschalk, R.,Zeegers, M. P. A.,Gielen, M.,de Groot, R. H. M. (2017). Associations between maternal long-chain polyunsaturated fatty acid concentrations and child cognition at 7 years of age: The MEFAB birth cohort Prostaglandins Leukot Essent Fatty Acids, 126(#issue#), 92-97 | Outcome
62 | Buccigrossi, V.,Ranucci, G.,Felisi, M. G.,Cantarutti, L.,Visentin, F.,Piacentini, D.,Spagnuolo, M. I.,Giaquinto, C.,Guarino, A. (2017). Early administration of prebiotics protects from respiratory infections and atopy by modifying intestinal microbial structure Journal of pediatric gastroenterology and nutrition, 64(#issue#), 973- | Publication status
63 | Buck, Miranda (2016). FOOD-SENSITIVE BABIES: DIETARY INVESTIGATION FOR BREASTFED BABIES Breastfeeding Review, 24(3), 12-12 | Publication status
64 | Buckley, J. P.,Engel, S. M.,Mendez, M. A.,Richardson, D. B.,Daniels, J. L.,Calafat, A. M.,Wolff, M. S.,Herring, A. H. (2016). Prenatal Phthalate Exposures and Childhood Fat Mass in a New York City Cohort Environ Health Perspect, 124(4), 507-13 | Intervention/exposure vs comparator
65 | Byrne, M. L.,Schwartz, O. S.,Simmons, J. G.,Sheeber, L.,Whittle, S.,Allen, N. B. (2018). Duration of Breastfeeding and Subsequent Adolescent Obesity: Effects of Maternal Behavior and Socioeconomic Status J Adolesc Health, 62(4), 471-479 | Study design
66 | Cabana, M. D. (2018). Does longer breastfeeding duration decrease the risk of asthma? Journal of Pediatrics, 195(#issue#), 1-2 | Publication status
67 | Cai, X.,Lian, F.,Kong, Y.,Huang, L.,Xu, L.,Wu, Y.,Ma, H.,Yang, L. (2019). Carotenoid metabolic (BCO1) polymorphisms and personal behaviors modify the risk of coronary atherosclerosis: a nested case-control study in Han Chinese with dyslipidaemia (2013-2016) Asia Pac J Clin Nutr, 28(1), 192-202 | Intervention/exposure vs comparator
68 | Campoy, C.,Nieto-Ruiz, A.,Arias, M.,Dieguez, E.,Herrmann, F.,Miranda, M. T.,De Castellar, R. (2018). Long-term influence of a milk fat globule membrane (MFGM)-enriched formula on language development in healthy children at 4 years old Journal of pediatric gastroenterology and nutrition, 66(#issue#), 929- | Publication status
69 | Campoy, C.,Nieto-Ruiz, A.,Sepulveda-Valbuena, N.,Dieguez, E.,Herrmann, F.,Miranda, M. T.,De Castellar, R. (2018). Association of early nutrition and gender with metabolic risk in healthy children at 4 years of age Annals of nutrition & metabolism, 73(#issue#), 44-45 | Publication status
70 | Campoy, C.,Ruiz, A. N. (2016). Nutritional intervention in early life influences the head circumference in healthy male children at 2.5 years Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 883 | Publication status
71 | Canani, R. B.,Nocerino, R.,Frediani, T.,Lucarelli, S.,Di Scala, C.,Varin, E.,Leone, L.,Muraro, A.,Agostoni, C. (2017). Amino Acid-based vs Formula in Cow’s Milk Allergy: Long-term Effects on Body Growth and Protein Metabolism J Pediatr Gastroenterol Nutr, 64(4), 632-638 | Intervention/exposure comparator
72 | Candy, D. C. A.,Van Ampting, M. T. J.,Oude Nijhuis, M. M.,Wopereis, H.,Butt, A. M.,Peroni, D. G.,West, C. E.,Vandenplas, Y.,Fox, A. T.,Harthoorn, L. F.,et al, (2016). Dietary management of non-ige mediated cow’s milk allergic infants with a synbiotics-supplemented amino acid-based formula: effects on faecal microbiota and clinical symptoms Journal of pediatric gastroenterology and nutrition, 63(#issue#), S402- | Outcome
73 | Cebolla-Boado, H.,Jimenez-Buedo, M.,Salazar, L. (2017). Avoiding selection bias without random assignment? The effect of breastfeeding on cognitive outcomes in China Soc Sci Med, 194(#issue#), 151-159 | Study design
74 | Cetinkaya, M.,Semerci, S. Y.,Ugurel, O.,Balik, D. T. (2017). Evaluation of the effect of palm olein free formula on intestinal flora and gastrointestinal tolerance in infants Journal of pediatric gastroenterology and nutrition, 65(#issue#), S320-S321 | Publication status
75 | Cetthakrikul, N.,Topothai, C.,Suphanchaimat, R.,Tisayaticom, K.,Limwattananon, S.,Tangcharoensathien, V. (2018). Childhood stunting in Thailand: when prolonged breastfeeding interacts with household poverty BMC Pediatr, 18(1), 395 | Study design
76 | Chan, D.,Goruk, S.,Becker, A. B.,Subbarao, P.,Mandhane, P. J.,Turvey, S. E.,Lefebvre, D.,Sears, M. R.,Field, C. J.,Azad, M. B. (2018). Adiponectin, leptin and insulin in breast milk: associations with maternal characteristics and infant body composition in the first year of life Int J Obes (Lond), 42(1), 36-43 | Intervention/exposure vs comparator
77 | Chan, K. C.,Tam, W. H.,Chan, M. H.,Chan, R. S.,Li, A. M. (2018). Vitamin D deficiency among healthy infants in Hong Kong: a pilot study Hong Kong Med J, 24 Suppl 3(3), 32-35 | Study design, Intervention/exposure vs comparator
78 | Chen, F.,Lin, Z.,Chen, R.,Norback, D.,Liu, C.,Kan, H.,Deng, Q.,Huang, C.,Hu, Y.,Zou, Z.,Liu, W.,Wang, J.,Lu, C.,Qian, H.,Yang, X.,Zhang, X.,Qu, F.,Sundell, J.,Zhang, Y.,Li, B.,Sun, Y.,Zhao, Z. (2018). The effects of PM2.5 on asthmatic and allergic diseases or symptoms in preschool children of six Chinese cities, based on China, Children, Homes and Health (CCHH) project Environ Pollut, 232(#issue#), 329-337 | Outcome
79 | Cheng, T. S.,Kwok, M. K.,Leung, G. M.,Schooling, C. M. (2018). The Associations of Breast Feeding with Infant Growth and Body Mass Index to 16 years: ‘Children of 1997’ Paediatr Perinat Epidemiol, 32(2), 200-209 | Outcome
80 | Cheng, T. S.,Loy, S. L.,Cheung, Y. B.,Chan, J. K.,Pang, W. W.,Godfrey, K. M.,Gluckman, P. D.,Kwek, K.,Saw, S. M.,Chong, Y. S.,Lee, Y. S.,Lek, N.,Yap, F. (2016). Sexually dimorphic response to feeding mode in the growth of infants Am J Clin Nutr, 103(2), 398-405 | Outcome
81 | Chiu, C. Y.,Liao, S. L.,Su, K. W.,Tsai, M. H.,Hua, M. C.,Lai, S. H.,Chen, L. C.,Yao, T. C.,Yeh, K. W.,Huang, J. L. (2016). Exclusive or Partial Breastfeeding for 6 Months Is Associated With Reduced Milk Sensitization and Risk of Eczema in Early Childhood: The PATCH Birth Cohort Study Medicine (Baltimore), 95(15), e3391 | Outcome
82 | Chiu, C. Y.,Liao, S. L.,Su, K. W.,Tsai, M. H.,Hua, M. C.,Lai, S. H.,Chen, L. C.,Yao, T. C.,Yeh, K. W.,Huang, J. L. (2016). Exclusive or Partial Breastfeeding for 6 Months Is Associated with Reduced Milk Sensitization and Risk of Eczema in Early Childhood Medicine (United States), 95(15), #Pages# | Outcome
83 | Choi, H. J.,Kang, S. K.,Chung, M. R. (2018). The relationship between exclusive breastfeeding and infant development: A 6- and 12-month follow-up study Early Hum Dev, 127(#issue#), 42-47 | Outcome
84 | Choi, J.,Chang, J. Y.,Hong, J.,Shin, S.,Park, J. S.,Oh, S. (2017). Low-Level Toxic Metal Exposure in Healthy Weaning-Age Infants: Association with Growth, Dietary Intake, and Iron Deficiency Int J Environ Res Public Health, 14(4), #Pages# | Study design
85 | Chowning, R.,Radmacher, P.,Lewis, S.,Serke, L.,Pettit, N.,Adamkin, D. H. (2016). A retrospective analysis of the effect of human milk on prevention of necrotizing enterocolitis and postnatal growth Journal of Perinatology, 36(3), 221-224 | Participant health
86 | Christensen, L. H.,Hoyer, B. B.,Pedersen, H. S.,Zinchuk, A.,Jonsson, B. A. G.,Lindh, C.,Durr, D. W.,Bonde, J. P.,Toft, G. (2016). Prenatal smoking exposure, measured as maternal serum cotinine, and children’s motor developmental milestones and motor function: A follow-up study Neurotoxicology, 53(#issue#), 236-245 | Outcome
87 | Chu, S.,Zhang, Y.,Jiang, Y.,Sun, W.,Zhu, Q.,Wang, B.,Jiang, F.,Zhang, J. (2017). Cesarean section without medical indication and risks of childhood allergic disorder, attenuated by breastfeeding Sci Rep, 7(1), 9762 | Outcome
88 | Civardi, E.,Garofoli, F.,Longo, S.,Mongini, M. E.,Grenci, B.,Mazzucchelli, I.,Angelini, M.,Castellazzi, A.,Fasano, F.,Grinzato, A.,Fanos, V.,Budelli, A.,Stronati, M. (2017). Safety, growth, and support to healthy gut microbiota by an infant formula enriched with functional compounds Clin Nutr, 36(1), 238-245 | Intervention/exposure vs comparator
89 | Claesson, Ing-Marie,Sydsjö, Gunilla,Olhager, Elisabeth,Oldin, Carin,Josefsson, Ann (2016). Effects of a Gestational Weight Gain Restriction Program for Obese Pregnant Women: Children’s Weight Development during the First Five Years of Life Childhood Obesity, 12(3), 162-170 | Intervention/exposure vs comparator
90 | Clark, K. M.,Li, M.,Zhu, B.,Liang, F.,Shao, J.,Zhang, Y.,Ji, C.,Zhao, Z.,Kaciroti, N.,Lozoff, B. (2017). Breastfeeding, Mixed, or Formula Feeding at 9 Months of Age and the Prevalence of Iron Deficiency and Iron Deficiency Anemia in Two Cohorts of Infants in China J Pediatr, 181(#issue#), 56-61 | Study design
91 | Cloutier, M. M.,Wiley, J. F.,Kuo, C. L.,Cornelius, T.,Wang, Z.,Gorin, A. A. (2018). Outcomes of an early childhood obesity prevention program in a low-income community: a pilot, randomized trial Pediatr Obes, 13(11), 677-685 | Intervention/exposure vs comparator
92 | Collell, R.,Closa-Monasterolo, R.,Ferre, N.,Luque, V.,Koletzko, B.,Grote, V.,Janas, R.,Verduci, E.,Escribano, J. (2016). Higher protein intake increases cardiac function parameters in healthy children: metabolic programming by infant nutrition-secondary analysis from a clinical trial Pediatr Res, 79(6), 880-8 | Intervention/exposure vs comparator
93 | Colombo, J.,Jill Shaddy, D.,Kerling, E. H.,Gustafson, K. M.,Carlson, S. E. (2017). Docosahexaenoic acid (DHA) and arachidonic acid (ARA) balance in developmental outcomes Prostaglandins Leukot Essent Fatty Acids, 121(#issue#), 52-56 | Intervention/exposure vs comparator
94 | Comba, A.,Demir, E.,Baris Eren, N. (2019). Nutritional status and related factors of schoolchildren in Corum, Turkey Public Health Nutr, 22(1), 122-131 | Study design
95 | Contarato, A. A.,Rocha, E. D.,Czarnobay, S. A.,Mastroeni, S. S.,Veugelers, P. J.,Mastroeni, M. F. (2016). Independent effect of type of breastfeeding on overweight and obesity in children aged 12-24 months Cad Saude Publica, 32(12), e00119015 | Intervention/exposure vs comparator
96 | Coo, H.,Fabrigar, L.,Davies, G.,Fitzpatrick, R.,Flavin, M. (2019). Are observed associations between a high maternal prepregnancy body mass index and offspring IQ likely to be causal? J Epidemiol Community Health, #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
97 | Corkins, M.,Czerkies, L. A.,Storm, H. M.,Sun, S.,Saavedra, J. M. (2016). Assessment of Growth of Infants Fed an Amino Acid-Based Formula Clin Med Insights Pediatr, 10(#issue#), 3-9 | Intervention/exposure vs comparator
98 | Costa, C. S.,Campagnolo, P. D.,Lumey, L. H.,Vitolo, M. R. (2017). Effect of maternal dietary counselling during the 1st year of life on glucose profile and insulin resistance at the age of 8 years: a randomised field trial Br J Nutr, 117(1), 134-141 | Intervention/exposure vs comparator
99 | Cronin, F. M.,Segurado, R.,McAuliffe, F. M.,Kelleher, C. C.,Tremblay, R. E. (2017). Gestational age and chronic ‘body-mind’ health problems in childhood: dose–response association and risk factors European Child and Adolescent Psychiatry, 26(1), 57-65 | Duplicate
100 | Cronin, Frances,Segurado, Ricardo,McAuliffe, Fionnuala,Kelleher, Cecily,Tremblay, Richard (2017). Gestational age and chronic ‘body-mind’ health problems in childhood: dose-response association and risk factors European Child & Adolescent Psychiatry, 26(1), 57-65 | Intervention/exposure vs comparator, Outcome
101 | Cunha, M. P. L.,Marques, R. C.,Dorea, J. G. (2018). Influence of Maternal Fish Intake on the Anthropometric Indices of Children in the Western Amazon Nutrients, 10(9), #Pages# | Outcome
102 | Cuppari, C.,Manti, S.,Salpietro, A.,Alterio, T.,Arrigo, T.,Leonardi, S.,Salpietro, C. (2016). Mode of delivery and atopic phenotypes: Old questions new insights? A retrospective study Immunobiology, 221(12), 1418-1423 | Outcome
103 | Dalmeijer, G. W.,Wijga, A. H.,Gehring, U.,Renders, C. M.,Koppelman, G. H.,Smit, H. A.,van Rossem, L. (2016). Fatty acid composition in breastfeeding and school performance in children aged 12 years Eur J Nutr, 55(7), 2199-207 | Outcome
104 | Daniels, S. R. (2018). BMI in early childhood Journal of Pediatrics, 202(#issue#), 2 | Publication status
105 | Davisse-Paturet, C.,Raherison, C.,Adel-Patient, K.,Divaret-Chauveau, A.,Bois, C.,Dufourg, M. N.,Lioret, S.,Charles, M. A.,de Lauzon-Guillain, B. (2019). Use of partially hydrolysed formula in infancy and incidence of eczema, respiratory symptoms or food allergies in toddlers from the ELFE cohort Pediatr Allergy Immunol, 30(6), 614-623 | Intervention/exposure vs comparator
106 | de Beer, M.,Vrijkotte, T. G.,Fall, C. H.,van Eijsden, M.,Osmond, C.,Gemke, R. J. (2016). Associations of Infant Feeding and Timing of Weight Gain and Linear Growth during Early Life with Childhood Blood Pressure: Findings from a Prospective Population Based Cohort Study PLoS One, 11(11), e0166281 | Intervention/exposure vs comparator
107 | De Regnier, R. A. (2017). Nutrition and brain development: it’s complicated Journal of Pediatrics, 183(#issue#), 1-2 | Publication status
108 | Delgado, C. A.,Munhoz, T. N.,Santos, I. S.,Barros, F. C.,Matijasevich, A. (2017). Prolonged breastfeeding for 24 months or more and mental health at 6 years of age: evidence from the 2004 Pelotas Birth Cohort Study, Brazil Child and Adolescent Mental Health, 22(4), 209-215 | Outcome
109 | den Dekker, H. T.,Sonnenschein-van der Voort, A. M.,Jaddoe, V. W.,Reiss, I. K.,de Jongste, J. C.,Duijts, L. (2016). Breastfeeding and asthma outcomes at the age of 6 years: The Generation R Study Pediatr Allergy Immunol, 27(5), 486-92 | Outcome
110 | Deoni, S.,Dean, D., 3rd,Joelson, S.,O’Regan, J.,Schneider, N. (2018). Early nutrition influences developmental myelination and cognition in infants and young children Neuroimage, 178(#issue#), 649-659 | Outcome
111 | Dhudasia, Miren B.,Flannery, Dustin D.,Mukhopadhyay, Sagori (2019). Early limited formula for breastfeeding infants: too much or just enough? Journal of Perinatology, 39(8), 1149-1152 | Publication status Outcome
112 | Diepeveen, F. B.,van Dommelen, P.,Oudesluys-Murphy, A. M.,Verkerk, P. H. (2017). Specific language impairment is associated with maternal and family factors Child Care Health Dev, 43(3), 401-405 | Outcome
113 | Ditomasso, Diane,Paiva, Andrea L. (2018). Neonatal Weight Matters: An Examination of Weight Changes in Full-Term Breastfeeding Newborns During the First 2 Weeks of Life Journal of Human Lactation, 34(1), 86-92 | Outcome, Intervention/exposure vs comparator
114 | Djurovic, D.,Milisavljevic, B.,Mugosa, B.,Lugonja, N.,Miletic, S.,Spasic, S.,Vrvic, M. (2017). Zinc concentrations in human milk and infant serum during the first six months of lactation J Trace Elem Med Biol, 41(#issue#), 75-78 | Intervention/exposure vs comparator
115 | Dogan, E.,Yilmaz, G.,Caylan, N.,Turgut, M.,Gokcay, G.,Oguz, M. M. (2018). Baby-led complementary feeding: Randomized controlled study Pediatr Int, 60(12), 1073-1080 | Intervention/exposure vs comparator
116 | Dogruel, D.,Bingol, G.,Altintas, D. U.,Yilmaz, M.,Kendirli, S. G. (2016). Prevalence of and risk factors for atopic dermatitis: A birth cohort study of infants in southeast Turkey Allergol Immunopathol (Madr), 44(3), 214-20 | Outcome
117 | Doǧruel, D.,Bingöl, G.,Altlntaş, D. U.,Yllmaz, M.,Kendirli, S. G. (2016). Clinical features of food allergy during the 1st year of life: The ADAPAR birth cohort study International Archives of Allergy and Immunology, 169(3), 171-180 | Outcome
118 | Doi, L.,Williams, A. J.,Frank, J. (2016). How has child growth around adiposity rebound altered in Scotland since 1990 and what are the risk factors for weight gain using the Growing Up in Scotland birth cohort 1? BMC Public Health, 16(1), 1081 | Outcome
119 | Donkor, H. M.,Grundt, J. H.,Juliusson, P. B.,Eide, G. E.,Hurum, J.,Bjerknes, R.,Markestad, T. (2017). Social and somatic determinants of underweight, overweight and obesity at 5 years of age: a Norwegian regional cohort study BMJ Open, 7(8), e014548 | Intervention/exposure vs comparator
120 | Duff, Elizabeth (2016). Infants born to obese women and fed with breast milk gain less weight than those fed with powdered milk within their first 6 months of life Midwifery, 43(#issue#), A4-A5 | Publication status
121 | Dugas, C.,Kearney, M.,Mercier, R.,Perron, J.,Tchernof, A.,Marc, I.,Weisnagel, S. J.,Robitaille, J. (2018). Early life nutrition, glycemic and anthropometric profiles of children exposed to gestational diabetes mellitus in utero Early Hum Dev, 118(#issue#), 37-41 | Intervention/exposure vs comparator
122 | Eagleton, S. G.,Hohman, E. E.,Verdiglione, N.,Birch, L. L.,Paul, I. M.,Savage, J. S. (2019). INSIGHT Study Maternal Return to Work and Infant Weight Outcomes Acad Pediatr, 19(1), 67-73 | Intervention/exposure vs comparator
123 | Eastman, C. J. (2016). Iodine in breastfeeding Aust Prescr, 39(1), 4 | Study design
124 | Edmonson, M. B.,Eickhoff, J. C. (2017). Weight Gain and Obesity in Infants and Young Children Exposed to Prolonged Antibiotic Prophylaxis JAMA Pediatr, 171(2), 150-156 | Outcome
125 | Ehrenthal, D. B.,Wu, P.,Trabulsi, J. (2016). Differences in the Protective Effect of Exclusive Breastfeeding on Child Overweight and Obesity by Mother’s Race Matern Child Health J, 20(9), 1971-9 | Outcome
126 | Ek, W. E.,Karlsson, T.,Hernándes, C. A.,Rask-Andersen, M.,Johansson, (2018). Breast-feeding and risk of asthma, hay fever, and eczema Journal of Allergy and Clinical Immunology, 141(3), 1157-1159.e9 | Publication status
127 | Elbert, N. J.,van Meel, E. R.,den Dekker, H. T.,de Jong, N. W.,Nijsten, T. E. C.,Jaddoe, V. W. V.,de Jongste, J. C.,Pasmans, Sgma,Duijts, L. (2017). Duration and exclusiveness of breastfeeding and risk of childhood atopic diseases Allergy, 72(12), 1936-1943 | Outcome
128 | Elbert, Niels J.,van Meel, Evelien R.,den Dekker, H. T.,de Jong, Nicolette W.,Nijsten, Tamar E. C.,Jaddoe, Vincent W. V.,de Jongste, Johan C.,Pasmans, Suzanne G. M. A.,Duijts, Liesbeth (2018). Duration and exclusiveness of breastfeeding and risk of childhood atopic diseases MIDIRS Midwifery Digest, 28(2), 234-234 | Outcome
129 | El-Heneidy, A.,Abdel-Rahman, M. E.,Mihala, G.,Ross, L. J.,Comans, T. A. (2018). Milk Other Than Breast Milk and the Development of Asthma in Children 3 Years of Age. A Birth Cohort Study (2006(-)2011) Nutrients, 10(11), #Pages# | Outcome
130 | El-Heneidy, Asmaa,Abdel-Rahman, Manar E.,Mihala, Gabor,Ross, Lynda J.,Comans, Tracy A. (2018). Milk Other Than Breast Milk and the Development of Asthma in Children 3 Years of Age. A Birth Cohort Study (2006–2011) Nutrients, 10(11), 1798 | Outcome
131 | Emmerson, A. J. B.,Dockery, K. E.,Mughal, M. Z.,Roberts, S. A.,Tower, C. L.,Berry, J. L. (2018). Vitamin D status of White pregnant women and infants at birth and 4 months in North West England: A cohort study Matern Child Nutr, 14(1), #Pages# | Study design
132 | Emmett, P. M. (2016). Dietary Patterns during Complementary Feeding and Later Outcomes Nestle Nutr Inst Workshop Ser, 85(#issue#), 145-54 | Publication status Intervention/exposure vs comparator
133 | Eny, K. M.,Chen, S.,Anderson, L. N.,Chen, Y.,Lebovic, G.,Pullenayegum, E.,Parkin, P. C.,Maguire, J. L.,Birken, C. S. (2018). Breastfeeding duration, maternal body mass index, and birth weight are associated with differences in body mass index growth trajectories in early childhood Am J Clin Nutr, 107(4), 584-592 | Intervention/exposure vs comparator
134 | Ercan, M.,Ozcetin, M.,Karaci, M.,Ozgurhan, G.,Yasar, A.,Guven, B. (2016). Relationship between newborn craniotabes and vitamin D status North Clin Istanb, 3(1), 15-21 | Intervention/exposure vs comparator
135 | Eroglu, C.,Demir, F.,Erge, D.,Uysal, P.,Kirdar, S.,Yilmaz, M.,Kurt Omurlu, I. (2019). The relation between serum vitamin D levels, viral infections and severity of attacks in children with recurrent wheezing Allergol Immunopathol (Madr), #volume#(#issue#), #Pages# | Study design
136 | Escribano, J.,Ferre, N.,Gispert-Llaurado, M.,Luque, V.,Rubio-Torrents, C.,Zaragoza-Jordana, M.,Polanco, I.,Codoner, F. M.,Chenoll, E.,Morera, M.,Moreno-Munoz, J. A.,Rivero, M.,Closa-Monasterolo, R. (2018). Bifidobacterium longum subsp infantis CECT7210-supplemented formula reduces diarrhea in healthy infants: a randomized controlled trial Pediatr Res, 83(6), 1120-1128 | Intervention/exposure vs comparator
137 | Escribano, J.,Luque, V.,Canals-Sans, J.,Ferre, N.,Koletzko, B.,Grote, V.,Weber, M.,Gruszfeld, D.,Szott, K.,Verduci, E.,Riva, E.,Brasselle, G.,Poncelet, P.,Closa-Monasterolo, R. (2016). Mental performance in 8-year-old children fed reduced protein content formula during the 1st year of life: safety analysis of a randomised clinical trial Br J Nutr, #volume#(#issue#), 1-9 | Intervention/exposure vs comparator
138 | Essau, C. A.,Sasagawa, S.,Lewinsohn, P. M.,Rohde, P. (2018). The impact of pre- and perinatal factors on psychopathology in adulthood J Affect Disord, 236(#issue#), 52-59 | Intervention/exposure vs comparator, Participant age
139 | Estevez-Gonzalez, M. D.,Santana Del Pino, A.,Henriquez-Sanchez, P.,Pena-Quintana, L.,Saavedra-Santana, P. (2016). Breastfeeding during the first 6 months of life, adiposity rebound and overweight/obesity at 8 years of age Int J Obes (Lond), 40(1), 10-3 | Already included in P/B24 search
140 | Faith, M. S.,Hittner, J. B.,Hurston, S. R.,Yin, J.,Greenspan, L. C.,Quesenberry, C. P., Jr.,Gunderson, E. P. (2019). Association of Infant Temperament With Subsequent Obesity in Young Children of Mothers With Gestational Diabetes Mellitus JAMA Pediatr, 173(5), 424-433 | Intervention/exposure vs comparator
141 | Fallah, R.,Kazemnejad, A.,Shoghli, A.,Vahabi, N. (2018). Growth velocity of children and its affective factors in northwestern Iran: A longitudinal study using marginal models Med J Islam Repub Iran, 32(#issue#), 72 | Intervention/exposure vs comparator
142 | Farahnak, Z.,Yuan, Y.,Vanstone, C. A.,Weiler, H. A. (2019). Maternal and neonatal red blood cell n-3 polyunsaturated fatty acids inversely associate with infant whole body fat mass assessed by dual-energy x-ray absorptiometry Appl Physiol Nutr Metab, #volume#(#issue#), #Pages# | Study design, Intervention/exposure vs comparator
143 | Farhangi, M. A. (2016). Nutritional status and feeding practices in pre-school children aged 1-5 years in rural and urban areas of East Azerbaijan- Iran Progress in Nutrition, 18(1), 16-21 | Study design, Intervention/exposure vs comparator
144 | Fatemi, M. J.,Fararouei, M.,Moravej, H.,Dianatinasab, M. (2018). Stunting and its associated factors among 6-7-year-old children in southern Iran: a nested case-control study Public Health Nutr, #volume#(#issue#), 1-8 | Confounders
145 | Fatemi, Mohammad Javad,Fararouei, Mohammad,Moravej, Hossein,Dianatinasab, Mostafa (2019). Stunting and its associated factors among 6-7-year-old children in southern Iran: a nested case-control study Public Health Nutrition, 22(1), 55-62 | Intervention/exposure vs comparator
146 | Feldman-Winter, L.,Burnham, L.,Grossman, X.,Matlak, S.,Chen, N.,Merewood, A. (2018). Weight gain in the first week of life predicts overweight at 2 years: A prospective cohort study Matern Child Nutr, 14(1), #Pages# | Outcome
147 | Fields, D.,Czerkies, L.,Sun, S.,Storm, H.,Saavedra, J.,Sorensen, R. (2016). A Randomized Controlled Trial Assessing Growth of Infants Fed a 100% Whey Extensively Hydrolyzed Formula Compared With a Casein-Based Extensively Hydrolyzed Formula Glob Pediatr Health, 3(#issue#), 2333794x16636613 | Intervention/exposure vs comparator
148 | Fiocchi, A.,Fierro, V.,La Marra, F.,Dahdah, L. A. (2016). The custom clearance of pro- and prebiotics in allergy prevention Annals of Allergy, Asthma and Immunology, 117(5), 465-467 | Publication status
149 | Fisher, H. R.,Lack, G.,Du Toit, G. (2019). Solid foods should be introduced into susceptible infants’ diets in early life-PRO Annals of Allergy, Asthma and Immunology, 122(6), 583-585 | Publication status
150 | Flaherman, V. J.,Schaefer, E. W.,Kuzniewicz, M. K.,Li, S.,Walsh, E.,Paul, I. M. (2017). Newborn Weight Loss During Birth Hospitalization and Breastfeeding Outcomes Through Age 1 Month J Hum Lact, 33(1), 225-230 | Outcome
151 | Fleddermann, M.,Demmelmair, H.,Grote, V.,Trisic, B.,Nikolic, T.,Koletzko, B. (2016). Growth during early infancy and anthropometry at 4 years of age: follow-up of the BeMIM study Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 680 | Publication status
152 | Fleddermann, M.,Demmelmair, H.,Hellmuth, C.,Grote, V.,Trisic, B.,Nikolic, T.,Koletzko, B. (2018). Association of infant formula composition and anthropometry at 4 years: Follow-up of a randomized controlled trial (BeMIM study) PLoS One, 13(7), e0199859 | Intervention/exposure vs comparator
153 | Flensborg-Madsen, T.,Mortensen, E. L. (2017). Predictors of motor developmental milestones during the first year of life Eur J Pediatr, 176(1), 109-119 | Outcome
154 | Flohr, C.,Henderson, A. J.,Kramer, M. S.,Patel, R.,Thompson, J.,Rifas-Shiman, S. L.,Yang, S.,Vilchuck, K.,Bogdanovich, N.,Hameza, M.,Martin, R. M.,Oken, E. (2018). Effect of an Intervention to Promote Breastfeeding on Asthma, Lung Function, and Atopic Eczema at Age 16 Years: Follow-up of the PROBIT Randomized Trial JAMA Pediatr, 172(1), e174064 | Outcome
155 | Flohr, C.,Kramer, M. S.,Patel, R.,Thompson, J.,Rifas-Shiman, S. L.,Yang, S.,Vilchuk, K.,Bogdanovich, N.,Hameza, M.,Martin, R. M.,et al, (2017). Does prolonged and exclusive breastfeeding reduce the risk of atopic eczema in adolescence? the PROBIT cluster-randomized trial in the Republic of Belarus British journal of dermatology, 177(#issue#), 159- | Publication status
156 | Foiles, A. M.,Kerling, E. H.,Wick, J. A.,Scalabrin, D. M.,Colombo, J.,Carlson, S. E. (2016). Formula with long-chain polyunsaturated fatty acids reduces incidence of allergy in early childhood Pediatr Allergy Immunol, 27(2), 156-61 | Intervention/exposure vs comparator
157 | Fonolla, J.,Maldonado-Lobon, J. A.,Gil-Campo, M.,Maldonado, J.,Flores, K.,Benavides, M. R.,Jaldo, R.,Del Barco, I. J.,Valero, A. D.,Lara, F.,et al, (2017). An infant formula enriched with the human milk strain Lactobacillus fermentum CECT5716 is safe and reduces dhiarrea incidences during first year of life Journal of pediatric gastroenterology and nutrition, 64(#issue#), 933- | Publication status
158 | Fonseca, P. C. A.,Carvalho, C. A.,Ribeiro, S. A. V.,Nobre, L. N.,Pessoa, M. C.,Ribeiro, A. Q.,Priore, S. E.,Franceschini, Sdcc (2017). Determinants of the mean growth rate of children under the age of six months: a cohort study Cien Saude Colet, 22(8), 2713-2726 | Outcome, Intervention/exposure vs comparator
159 | Forbes, J. D.,Azad, M. B.,Vehling, L.,Tun, H. M.,Konya, T. B.,Guttman, D. S.,Field, C. J.,Lefebvre, D.,Sears, M. R.,Becker, A. B.,Mandhane, P. J.,Turvey, S. E.,Moraes, T. J.,Subbarao, P.,Scott, J. A.,Kozyrskyj, A. L. (2018). Association of Exposure to Formula in the Hospital and Subsequent Infant Feeding Practices With Gut Microbiota and Risk of Overweight in the First Year of Life JAMA Pediatr, 172(7), e181161 | Outcome
160 | Fortes, C.,Mastroeni, S.,Mannooranparampil, T. J.,Di Lallo, D. (2019). Pre-natal folic acid and iron supplementation and atopic dermatitis in the first 6 years of life Arch Dermatol Res, 311(5), 361-367 | Outcome
161 | Foster, B. A.,Escaname, E.,Powell, T. L.,Larsen, B.,Siddiqui, S. K.,Menchaca, J.,Aquino, C.,Ramamurthy, R.,Hale, D. E. (2017). Randomized Controlled Trial of DHA Supplementation during Pregnancy: Child Adiposity Outcomes Nutrients, 9(6), #Pages# | Confounders
162 | Gaffney, K. F.,Brito, A. V.,Kitsantas, P.,Kermer, D. A. (2016). Early Feeding Practices and Weight Status at One Year of Age: A Comparison of Hispanic Immigrant Mother-Infant Dyads with Participants of the Infant Feeding Practices Study II Child Obes, 12(5), 384-91 | Outcome
163 | Gahagan, S.,Delker, E.,Blanco, E.,Burrows, R.,Lozoff, B. (2019). Randomized Controlled Trial of Iron-Fortified versus Low-Iron Infant Formula: Developmental Outcomes at 16 Years J Pediatr, 212(#issue#), 124-130.e1 | Intervention/exposure vs comparator
164 | Gahagan, S.,Delker, E.,Castillo, M.,Lozoff, B. (2017). Iron-fortified vs low-iron infant formula: cognitive outcomes at 10 and 16 years American journal of hematology, 92(8), E231- | Study design
165 | Galland, B.,Taylor, B.,Gray, A.,Heath, A.,Lawrence, J.,Sayers, R.,Cameron, S.,Hanna, M.,Dale, K.,Coppell, K.,et al, (2016). Early life prevention of obesity by targeting sleep, or food and activity: a randomized controlled trial Sleep, 39(#issue#), A339-A340 | Publication status
166 | Gallier, S.,Xia, Y.,Rowan, A.,Wang, B. (2018). Milk fat globule membrane as a source of gangliosides and phospholipids in infancy to support brain development and healthy growth Journal of pediatric gastroenterology and nutrition, 66(#issue#), 942- | Publication status
167 | Gallo, S.,Hazell, T.,Vanstone, C. A.,Agellon, S.,Jones, G.,L’Abbé, M.,Rodd, C.,Weiler, H. A. (2016). Vitamin D supplementation in breastfed infants from Montréal, Canada: 25-hydroxyvitamin D and bone health effects from a follow-up study at 3 years of age Osteoporosis International, #volume#(#issue#), 1-8 | Intervention/exposure vs comparator
168 | Gallo, S.,Hazell, T.,Vanstone, C. A.,Agellon, S.,Jones, G.,L’Abbe, M.,Rodd, C.,Weiler, H. A. (2016). Vitamin D supplementation in breastfed infants from Montreal, Canada: 25-hydroxyvitamin D and bone health effects from a follow-up study at 3 years of age Osteoporos Int, 27(8), 2459-66 | Intervention/exposure vs comparator
169 | Gao, X.,Yan, Y.,Zeng, G.,Sha, T.,Liu, S.,He, Q.,Chen, C.,Li, L.,Xiang, S.,Li, H.,Tan, S.,Yan, Q. (2019). Influence of prenatal and early-life exposures on food allergy and eczema in infancy: a birth cohort study BMC Pediatr, 19(1), 239 | Intervention/exposure vs comparator
170 | Geohagan, J.,de Gaston, D.,Sadler, A.,Palmer, P. (2018). Does oral maternal Vitamin D supplementation normalize the Vitamin D level in exclusively breastfed infants? J Okla State Med Assoc, 111(10), 870-871 | Study design
171 | Georgieva, M.,Manios, Y.,Rasheva, N.,Pancheva, R.,Dimitrova, E.,Stoeva, T. D.,Schaafsma, A. (2016). Effects of carob-bean gum thickened formulas on infants’ reflux, growth and tolerance indices Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 468 | Intervention/exposure vs comparator
172 | Ghaemmaghami, P.,Ayatollahi, S. M. T.,Alinejad, V.,Sharafi, Z. (2018). Growth curves and their associated weight and height factors in children from birth to 4 years old in West Azerbaijan Province, northwest Iran Arch Pediatr, 25(6), 389-393 | OutcomeOutcome
173 | Gianni, M. L.,Roggero, P.,Baudry, C.,Fressange-Mazda, C.,Galli, C.,Agostoni, C.,le Ruyet, P.,Mosca, F. (2018). An infant formula containing dairy lipids increased red blood cell membrane Omega 3 fatty acids in 4 month-old healthy newborns: a randomized controlled trial BMC Pediatr, 18(1), 53 | Group size
174 | Gianni, M. L.,Roggero, P.,Baudry, C.,Fressange-Mazda, C.,le Ruyet, P.,Mosca, F. (2018). No effect of adding dairy lipids or long chain polyunsaturated fatty acids on formula tolerance and growth in full term infants: a randomized controlled trial BMC Pediatr, 18(1), 10 | Group size
175 | Gianni, M. L.,Roggero, P.,Baudry, C.,Galli, C.,Le Ruyet, P.,Mosca, F. (2016). Dairy lipids in infant formula: impact on the Omega-3 fatty acid content in membrane phospholipids of red blood cells in healthy term infants Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 656 | Study design
176 | Gianni, M. L.,Roggero, P.,Baudry, C.,Le Ruyet, P.,Mosca, F. (2016). Dairy lipids in infant formula: impact on growth and gastrointestinal tolerance in healthy infants Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 831 | Study design
177 | Gibbs, B. G.,Forste, R.,Lybbert, E. (2018). Breastfeeding, Parenting, and Infant Attachment Behaviors Matern Child Health J, 22(4), 579-588 | Outcome
178 | Gibson, L. A.,Hernandez Alava, M.,Kelly, M. P.,Campbell, M. J. (2017). The effects of breastfeeding on childhood BMI: a propensity score matching approach J Public Health (Oxf), 39(4), e152-e160 | Outcome
179 | Gibson, L.,Porter, M. (2018). Drinking or Smoking While Breastfeeding and Later Cognition in Children Pediatrics, 142(2), #Pages# | Outcome
180 | Gillette, M. T.,Lohman, B. J.,Neppl, T. K. (2017). Lower levels of maternal capital in early life predict offspring obesity in adulthood Ann Hum Biol, 44(3), 252-260 | Intervention/exposure vs comparator
181 | Girard, L. C.,Doyle, O.,Tremblay, R. E. (2017). Breastfeeding, Cognitive and Noncognitive Development in Early Childhood: A Population Study Pediatrics, 139(4), #Pages# | Outcome
182 | Girard, L. C.,Farkas, C. (2019). Breastfeeding and behavioural problems: Propensity score matching with a national cohort of infants in Chile BMJ Open, 9(2), e025058 | Outcome
183 | Girard, L. C.,Tremblay, R. E.,Nagin, D.,Cote, S. M. (2019). Development of Aggression Subtypes from Childhood to Adolescence: a Group-Based Multi-Trajectory Modelling Perspective J Abnorm Child Psychol, 47(5), 825-838 | Intervention/exposure vs comparator, Outcome
184 | Girard, Lisa-Christine,Doyle, Orla,Tremblay, Richard E. (2018). Breastfeeding and externalising problems: a quasi-experimental design with a national cohort European Child & Adolescent Psychiatry, 27(7), 877-884 | Outcome
185 | Godleski, S. A.,Shisler, S.,Eiden, R. D.,Huestis, M. A. (2018). Co-use of tobacco and marijuana during pregnancy: Pathways to externalizing behavior problems in early childhood Neurotoxicol Teratol, 69(#issue#), 39-48 | Study design, Intervention/exposure vs comparator, Outcome
186 | Goetz, A. R.,Mara, C. A.,Stark, L. J. (2018). Greater Breastfeeding in Early Infancy Is Associated with Slower Weight Gain among High Birth Weight Infants J Pediatr, 201(#issue#), 27-33.e4 | Outcome
187 | Golding, J.,Gregory, S.,Ellis, G.,Nunes, T.,Bryant, P.,Iles-Caven, Y.,Nowicki, S. (2019). Maternal Prenatal External Locus of Control and Reduced Mathematical and Science Abilities in Their Offspring: A Longitudinal Birth Cohort Study Front Psychol, 10(#issue#), 194 | Intervention/exposure vs comparator
188 | Golding, J.,Iles-Caven, Y.,Ellis, G.,Gregory, S.,Nowicki, S. (2019). The relationship between parental locus of control and adolescent obesity: a longitudinal pre-birth cohort Int J Obes (Lond), 43(4), 724-734 | Intervention/exposure vs comparator
189 | Goldsmith, A. J.,Koplin, J. J.,Lowe, A. J.,Tang, M. L.,Matheson, M. C.,Robinson, M.,Peters, R.,Dharmage, S. C.,Allen, K. J. (2016). Formula and breast feeding in infant food allergy: A population-based study J Paediatr Child Health, 52(4), 377-84 | Study design
190 | Goncalves, V. S. S.,Silva, S. A.,Andrade, R. C. S.,Spaniol, A. M.,Nilson, E. A. F.,Moura, I. F. (2019). Food intake and underweight markers in children under 6 months old monitored via the Food and Nutrition Surveillance System, Brazil, 2015 Epidemiol Serv Saude, 28(2), e2018358 | Language, Study design
191 | Gorohi, F.,Shiemorteza, M.,Nori, M. M. (2018). Comparison of height, weight and head circumference index and the incidence of infectious and gastrointestinal diseases in breast-fed and formula-fed infants at 0 to 1 year old in Bu-Ali Sina Hospital Biomedical and Pharmacology Journal, 11(3), 1717-1730 | OutcomeStudy design
192 | Grace, T.,Oddy, W.,Bulsara, M.,Hands, B. (2017). Breastfeeding and motor development: A longitudinal cohort study Hum Mov Sci, 51(#issue#), 9-16 | Intervention/exposure vs comparator
193 | Graulau, R. E.,Banna, J.,Campos, M.,Gibby, C. L. K.,Palacios, C. (2019). Amount, Preparation and Type of Formula Consumed and Its Association with Weight Gain in Infants Participating in the WIC Program in Hawaii and Puerto Rico Nutrients, 11(3), #Pages# | Intervention/exposure vs comparator
194 | Gridneva, Z.,Hepworth, A. R.,Ward, L. C.,Lai, C. T.,Hartmann, P. E.,Geddes, D. T. (2017). Determinants of body composition in breastfed infants using bioimpedance spectroscopy and ultrasound skinfolds-methods comparison Pediatr Res, 81(3), 423-433 | Outcome
195 | Gridneva, Z.,Kugananthan, S.,Rea, A.,Lai, C. T.,Ward, L. C.,Murray, K.,Hartmann, P. E.,Geddes, D. T. (2018). Human Milk Adiponectin and Leptin and Infant Body Composition over the First 12 Months of Lactation Nutrients, 10(8), #Pages# | Intervention/exposure vs comparator
196 | Gridneva, Z.,Rea, A.,Hepworth, A. R.,Ward, L. C.,Lai, C. T.,Hartmann, P. E.,Geddes, D. T. (2018). Relationships between Breastfeeding Patterns and Maternal and Infant Body Composition over the First 12 Months of Lactation Nutrients, 10(1), #Pages# | Intervention/exposure vs comparator
197 | Gridneva, Z.,Rea, A.,Tie, W. J.,Lai, C. T.,Kugananthan, S.,Ward, L. C.,Murray, K.,Hartmann, P. E.,Geddes, D. T. (2019). Carbohydrates in Human Milk and Body Composition of Term Infants during the First 12 Months of Lactation Nutrients, 11(7), #Pages# | Intervention/exposure vs comparator
198 | Grillo, L. P.,Gigante, D. P.,Horta, B. L.,de Barros, F. C. (2016). Childhood stunting and the metabolic syndrome components in young adults from a Brazilian birth cohort study Eur J Clin Nutr, 70(5), 548-53 | Intervention/exposure vs comparator
199 | Grimshaw, K. E.,Bryant, T.,Oliver, E. M.,Martin, J.,Maskell, J.,Kemp, T.,Clare Mills, E. N.,Foote, K. D.,Margetts, B. M.,Beyer, K.,Roberts, G. (2015). Incidence and risk factors for food hypersensitivity in UK infants: results from a birth cohort study Clin Transl Allergy, 6(#issue#), 1 | Outcome
200 | Grip, T.,Dyrlund, T. F.,Ahonen, L.,Domellof, M.,Hernell, O.,Hyotylainen, T.,Knip, M.,Lonnerdal, B.,Oresic, M.,Timby, N. (2016). Serum lipid profile in infants fed formula supplemented with a bovine milk fat globule membrane fraction Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 676 | Study design
201 | Grip, T.,Dyrlund, T. S.,Ahonen, L.,Domellof, M.,Hernell, O.,Hyotylainen, T.,Knip, M.,Lonnerdal, B.,Oresic, M.,Timby, N. (2018). Serum, plasma and erythrocyte membrane lipidomes in infants fed formula supplemented with bovine milk fat globule membranes Pediatr Res, 84(5), 726-732 | Intervention/exposure vs comparator
202 | Grip, T.,Hernell, O.,Lonnerdal, B.,Domellof, M.,Timby, N. (2016). Plasma metabolome in infants fed formula supplemented with milk fat globule membranes Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 660 | Study design
203 | Grote, V.,Theurich, M.,Luque, V.,Gruszfeld, D.,Verduci, E.,Xhonneux, A.,Koletzko, B. (2018). Complementary Feeding, Infant Growth, and Obesity Risk: Timing, Composition, and Mode of Feeding Nestle Nutr Inst Workshop Ser, 89(#issue#), 93-103 | Publication status
204 | Gruszfeld, D.,Weber, M.,Gradowska, K.,Socha, P.,Grote, V.,Xhonneux, A.,Dain, E.,Verduci, E.,Riva, E.,Closa-Monasterolo, R.,Escribano, J.,Koletzko, B. (2016). Association of early protein intake and pre-peritoneal fat at five years of age: Follow-up of a randomized clinical trial Nutr Metab Cardiovasc Dis, 26(9), 824-32 | Intervention/exposure vs comparator
205 | Guerrero, A. D.,Mao, C.,Fuller, B.,Bridges, M.,Franke, T.,Kuo, A. A. (2016). Racial and Ethnic Disparities in Early Childhood Obesity: Growth Trajectories in Body Mass Index J Racial Ethn Health Disparities, 3(1), 129-37 | Outcome
206 | Gunderson, E. P.,Greenspan, L. C.,Faith, M. S.,Hurston, S. R.,Quesenberry, C. P., Jr. (2018). Breastfeeding and growth during infancy among offspring of mothers with gestational diabetes mellitus: a prospective cohort study Pediatr Obes, 13(8), 492-504 | Intervention/exposure vs comparator
207 | Gunnarsdottir, J.,Cnattingius, S.,Lundgren, M.,Selling, K.,Hogberg, U.,Wikstrom, A. K. (2018). Prenatal exposure to preeclampsia is associated with accelerated height gain in early childhood PLoS One, 13(2), e0192514 | Intervention/exposure vs comparator
208 | Gunnell, L.,Neher, J.,Safranek, S.,Guthmann, R. (2016). Does breastfeeding affect the risk of childhood obesity? Journal of Family Practice, 65(12), 931-932 | Publication status
209 | Gunnell, Lindsay,Neher, Jon,Safranek, Sarah (2016). Q / Does breastfeeding affect the risk of childhood obesity? Journal of Family Practice, 65(12), 931-932 | Publication status
210 | Hakola, L.,Takkinen, H. M.,Niinisto, S.,Ahonen, S.,Nevalainen, J.,Veijola, R.,Ilonen, J.,Toppari, J.,Knip, M.,Virtanen, S. M. (2018). Infant Feeding in Relation to the Risk of Advanced Islet Autoimmunity and Type 1 Diabetes in Children With Increased Genetic Susceptibility: A Cohort Study Am J Epidemiol, 187(1), 34-44 | Outcome
211 | Halipchuk, J.,Temple, B.,Dart, A.,Martin, D.,Sellers, E. A. C. (2018). Prenatal, Obstetric and Perinatal Factors Associated With the Development of Childhood-Onset Type 2 Diabetes Can J Diabetes, 42(1), 71-77 | Outcome
212 | Han, D. H.,Shin, J. M.,An, S.,Kim, J. S.,Kim, D. Y.,Moon, S.,Kim, J. S.,Cho, J. S.,Kim, S. W.,Kim, Y. H.,Roh, H. J.,Shim, W. S.,Rha, K. S.,Kim, S. W.,Lee, S. S.,Kim, D. W.,Cho, K. S.,Yim, H. J.,Park, S. K.,Rhee, C. S. (2019). Long-term Breastfeeding in the Prevention of Allergic Rhinitis: Allergic Rhinitis Cohort Study for Kids (ARCO-Kids Study) Clin Exp Otorhinolaryngol, 12(3), 301-307 | Outcome
213 | Hand, S.,Jones, K.,Doull, I. (2016). Age of weaning and asthma and atopy in young adults European respiratory journal. Conference: european respiratory society annual congress 2016. United kingdom. Conference start: 20160903. Conference end: 20160907, 48(no pagination), #Pages# | Publication status
214 | Hara, K.,Ikeda, K.,Hasegawa, T.,Koyama, Y.,Wada, Y. (2017). Serum 25-Hydroxyvitamin D3 levels of one-month-old term infants in Tokyo using liquid chromatography tandem mass spectrometry International journal of pediatric endocrinology. Conference: 9th biennial scientific meeting of the asia pacific paediatric endocrine society, APPES and the 50th annual meeting of the japanese society for pediatric endocrinology, JSPE. Japan, 2017(Supplement 1) (no pagination), #Pages# | Study design
215 | Hara, K.,Ikeda, K.,Koyama, Y.,Wada, Y.,Hasegawa, T. (2018). Serum 25-hydroxyvitamin D3 levels of one-month-old term infants in Tokyo using liquid chromatography tandem mass spectrometry Acta Paediatrica, International Journal of Paediatrics, 107(3), 532-533 | Study design
216 | Harding, K. L.,Aguayo, V. M.,Webb, P. (2018). Birthweight and feeding practices are associated with child growth outcomes in South Asia Matern Child Nutr, 14 Suppl 4(#issue#), e12650 | Study design Country
217 | Harrison, Michelle,Brodribb, Wendy,Davies, Peter S. W.,Hepworth, Julie (2019). Relationships between parental feeding practices, infant weight concern, infant dietary behaviour and body weight: Findings from the Feeding A Baby (FAB) Study Obesity Research & Clinical Practice, 13(1), 86-86 | Publication status
218 | Hawkins, S. S.,Baum, C. F.,Rifas-Shiman, S. L.,Oken, E.,Taveras, E. M. (2019). Examining Associations between Perinatal and Postnatal Risk Factors for Childhood Obesity Using Sibling Comparisons Child Obes, 15(4), 254-261 | Outcome
219 | Hazell, T. J.,Gallo, S.,Vanstone, C. A.,Agellon, S.,Rodd, C.,Weiler, H. A. (2017). Vitamin D supplementation trial in infancy: body composition effects at 3 years of age in a prospective follow-up study from Montreal Pediatr Obes, 12(1), 38-47 | Intervention/exposure vs comparator
220 | Hazrati, S.,Khan, F.,Huddleston, K.,De La Cruz, F.,Deeken, J. F.,Fuller, A.,Wong, W. S. W.,Niederhuber, J. E.,Hourigan, S. K. (2019). Clinical and social factors associated with excess weight in Hispanic and non-Hispanic White children Pediatr Res, 85(3), 256-261 | Study design, Intervention/exposure vs comparator
221 | Heerman, W. J.,Sommer, E. C.,Slaughter, J. C.,Samuels, L. R.,Martin, N. C.,Barkin, S. L. (2019). Predicting Early Emergence of Childhood Obesity in Underserved Preschoolers J Pediatr, #volume#(#issue#), #Pages# | Outcome
222 | Hellmuth, C.,Uhl, O.,Demmelmair, H.,Grunewald, M.,Auricchio, R.,Castillejo, G.,Korponay-Szabo, I. R.,Polanco, I.,Roca, M.,Vriezinga, S. L.,Werkstetter, K. J.,Koletzko, B.,Mearin, M. L.,Kirchberg, F. F. (2018). The impact of human breast milk components on the infant metabolism PLoS One, 13(6), e0197713 | Intervention/exposure vs comparator
223 | Herberth, G.,Pierzchalski, A.,Feltens, R.,Bauer, M.,Röder, S.,Olek, S.,Hinz, D.,Borte, M.,von Bergen, M.,Lehmann, I. (2017). Prenatal phthalate exposure associates with low regulatory T-cell numbers and atopic dermatitis in early childhood: Results from the LINA mother-child study Journal of Allergy and Clinical Immunology, 139(4), 1376-1379.e8 | Outcome
224 | Hewison, Martin,Wagner, Carol L.,Hollis, Bruce W.,Roth, Daniel E.,Gernand, Alison D.,Al Mahmud, Abdullah (2018). Vitamin D Supplementation in Pregnancy and Lactation and Infant Growth #journal#, 379(#issue#), 1880-1881 | Study design
225 | Hirata, M.,Kusakawa, I.,Ohde, S.,Yamanaka, M.,Yoda, H. (2017). Risk factors of infant anemia in the perinatal period Pediatr Int, 59(4), 447-451 | Study design
226 | Hisada, A.,Yoshinaga, J.,Zhang, J.,Kato, T.,Shiraishi, H.,Shimodaira, K.,Okai, T.,Ariki, N.,Komine, Y.,Shirakawa, M.,Noda, Y.,Kato, N. (2017). Maternal Exposure to Pyrethroid Insecticides during Pregnancy and Infant Development at 18 Months of Age Int J Environ Res Public Health, 14(1), #Pages# | Intervention/exposure vs comparator
227 | Hoeke, H.,Roeder, S.,Mueller, A.,Bertsche, T.,Borte, M.,Rolle-Kampczyk, U.,von Bergen, M.,Wissenbach, D. K. (2016). Biomonitoring of prenatal analgesic intake and correlation with infantile anti-aeroallergens IgE Allergy, 71(6), 901-6 | Outcome
228 | Hoffman, D. R.,Harris, C. L.,Wampler, J. L.,Patterson, A. C.,Berseth, C. L. (2019). Growth, tolerance, and DHA and ARA status of healthy term infants receiving formula with two different ARA concentrations: Double-blind, randomized, controlled trial Prostaglandins Leukotrienes and Essential Fatty Acids, 146(#issue#), 19-27 | Intervention/exposure vs comparator
229 | Hohman, E. E.,Savage, J. S.,Birch, L. L.,Beiler, J. S.,Paul, I. M. (2018). Pacifier Use and Early Life Weight Outcomes in the Intervention Nurses Start Infants Growing on Healthy Trajectories Study Child Obes, 14(1), 58-66 | Intervention/exposure vs comparator
230 | Hohman, E. E.,Savage, J. S.,Paul, I. M.,Birch, L. L. (2016). INSIGHT study parenting intervention to prevent childhood obesity improves patterns of dietary exposures in infants FASEB journal, 30(#issue#), #Pages# | Publication status
231 | Hojat, M.,Mogarab, V.,Jahromi, H. K. (2016). The study of growth differences of infants less than 6 months which have used breast milk and infant formula along with breast milk International Journal of Pharmaceutical Research and Allied Sciences, 5(4), 108-119 | Study design
232 | Holmsen, S. T.,Bakkebo, T.,Seferowicz, M.,Retterstol, K. (2017). Statins and breastfeeding in familial hypercholesterolaemia Tidsskr Nor Laegeforen, 137(10), 686-687 | Outcome
233 | Horodynski, M. A.,Pierce, S. J.,Reyes-Gastelum, D.,Olson, B.,Shattuck, M. (2017). Feeding Practices and Infant Growth: Quantifying the Effects of Breastfeeding Termination and Complementary Food Introduction on BMI z-Score Growth Velocity through Growth Curve Models Child Obes, 13(6), 490-498 | Outcome
234 | Horta, B. L.,Victora, C. G.,Franca, G. V. A.,Hartwig, F. P.,Ong, K. K.,Rolfe, E. L.,Magalhaes, E. I. S.,Lima, N. P.,Barros, F. C. (2018). Breastfeeding moderates FTO related adiposity: a birth cohort study with 30 years of follow-up Sci Rep, 8(1), 2530 | Intervention/exposure vs comparator
235 | Hu, C.,Duijts, L.,Erler, N. S.,Elbert, N. J.,Piketty, C.,Bourdes, V.,Blanchet-Rethore, S.,de Jongste, J. C.,Pasmans, Sgma,Felix, J. F.,Nijsten, T. (2019). Most associations of early-life environmental exposures and genetic risk factors poorly differentiate between eczema phenotypes: the Generation R Study Br J Dermatol, #volume#(#issue#), #Pages# | Outcome
236 | Huang, J. G.,Chan, S. H.,Lee, L. Y. (2018). The Influence of Ethnicity on Exclusively Breast-Fed Infants’ Anthropometry in a Multiethnic Asian Population Ann Acad Med Singapore, 47(6), 208-215 | Outcome
237 | Huang, J.,Vaughn, M. G.,Kremer, K. P. (2016). Breastfeeding and child development outcomes: an investigation of the nurturing hypothesis Matern Child Nutr, 12(4), 757-67 | Outcome
238 | Huang, J.,Zhang, Z.,Wu, Y.,Wang, Y.,Wang, J.,Zhou, L.,Ni, Z.,Hao, L.,Yang, N.,Yang, X. (2018). Early feeding of larger volumes of formula milk is associated with greater body weight or overweight in later infancy Nutr J, 17(1), 12 | Intervention/exposure vs comparator
239 | Huang, T.,Yue, Y.,Wang, H.,Zheng, J.,Chen, Z.,Chen, T.,Zhang, M.,Wang, S. (2019). Infant Breastfeeding and Behavioral Disorders in School-Age Children Breastfeed Med, 14(2), 115-120 | Study design
240 | Huang, X.,Chang, J.,Feng, W.,Xu, Y.,Xu, T.,Tang, H.,Wang, H.,Pan, X. (2016). Development of a New Growth Standard for Breastfed Chinese Infants: What Is the Difference from the WHO Growth Standards? PLoS One, 11(12), e0167816 | Outcome
241 | Huet, F.,Abrahamse-Berkeveld, M.,Tims, S.,Simeoni, U.,Beley, G.,Savagner, C.,Vandenplas, Y.,Hourihane, J. O. (2016). Partly Fermented Infant Formulae With Specific Oligosaccharides Support Adequate Infant Growth and Are Well-Tolerated J Pediatr Gastroenterol Nutr, 63(4), e43-53 | Intervention/exposure vs comparator
242 | Hui, L. L.,Kwok, M. K.,Nelson, E. A. S.,Lee, S. L.,Leung, G. M.,Schooling, C. M. (2018). The association of breastfeeding with insulin resistance at 17 years: Prospective observations from Hong Kong’s “Children of 1997” birth cohort Matern Child Nutr, 14(1), #Pages# | Outcome
243 | Hui, L. L.,Kwok, M. K.,Nelson, E. A. S.,Lee, S. L.,Leung, G. M.,Schooling, C. M. (2019). Breastfeeding in Infancy and Lipid Profile in Adolescence Pediatrics, 143(5), #Pages# | Outcome
244 | Hui, L. L.,Lam, H. S.,Lau, E. Y. Y.,Nelson, E. A. S.,Wong, T. W.,Fielding, R. (2016). Prenatal dioxin exposure and neurocognitive development in Hong Kong 11-year-old children Environ Res, 150(#issue#), 205-212 | Outcome
245 | Hui, L. L.,Lee, S. L.,Kwok, M. K.,Yu, C. W.,Schooling, C. M. (2018). Formula-feeding and the risk of type-2 diabetes mellitus among Hong Kong adolescents Hong Kong Med J, 24 Suppl 4(4), 20-23 | Outcome
246 | Hui, L. L.,Li, A. M.,Nelson, E. A. S.,Leung, G. M.,Lee, S. L.,Schooling, C. M. (2018). In utero exposure to gestational diabetes and adiposity: does breastfeeding make a difference? Int J Obes (Lond), 42(7), 1317-1325 | Outcome
247 | Hummel, S.,Beyerlein, A.,Tamura, R.,Uusitalo, U.,Andren Aronsson, C.,Yang, J.,Riikonen, A.,Lernmark, A.,Rewers, M. J.,Hagopian, W. A.,She, J. X.,Simell, O. G.,Toppari, J.,Ziegler, A. G.,Akolkar, B.,Krischer, J. P.,Virtanen, S. M.,Norris, J. M. (2017). First Infant Formula Type and Risk of Islet Autoimmunity in The Environmental Determinants of Diabetes in the Young (TEDDY) Study Diabetes Care, 40(3), 398-404 | Outcome
248 | Huynh, D.,Condo, D.,Gibson, R.,Muhlhausler, B.,Ryan, P.,Skeaff, S.,Makrides, M.,Zhou, S. J. (2017). Iodine status of postpartum women and their infants in Australia after the introduction of mandatory iodine fortification Br J Nutr, 117(12), 1656-1662 | Study design, Intervention/exposure vs comparator
249 | Iguacel, I.,Chung, A.,Gearon, E.,Moreno, L. A.,Peeters, A.,Backholer, K. (2018). Influence of early-life risk factors on socioeconomic inequalities in weight gain J Public Health (Oxf), 40(4), e447-e455 | Intervention/exposure vs comparator
250 | Iguacel, I.,Escartin, L.,Fernandez-Alvira, J. M.,Iglesia, I.,Labayen, I.,Moreno, L. A.,Samper, M. P.,Rodriguez, G. (2018). Early life risk factors and their cumulative effects as predictors of overweight in Spanish children Int J Public Health, 63(4), 501-512 | Intervention/exposure vs comparator
251 | Iguacel, I.,Fernandez-Alvira, J. M.,Labayen, I.,Moreno, L. A.,Samper, M. P.,Rodriguez, G. (2018). Social vulnerabilities as determinants of overweight in 2-, 4- and 6-year-old Spanish children Eur J Public Health, 28(2), 289-295 | Intervention/exposure vs comparator
252 | Iguacel, I.,Monje, L.,Cabero, M. J.,Moreno Aznar, L. A.,Samper, M. P.,Rodriguez-Palmero, M.,Rivero, M.,Rodriguez, G. (2019). Feeding patterns and growth trajectories in breast-fed and formula-fed infants during the introduction of complementary food Nutr Hosp, 36(4), 777-785 | Intervention/exposure vs comparator
253 | Isaacs, D. (2016). Hydrolysed formula not shown to prevent allergy J Paediatr Child Health, 52(8), 850-1 | Publication status, Study design
254 | Iszatt, N.,Stigum, H.,Govarts, E.,Murinova, L. P.,Schoeters, G.,Trnovec, T.,Legler, J.,Thomsen, C.,Koppen, G.,Eggesbo, M. (2016). Perinatal exposure to dioxins and dioxin-like compounds and infant growth and body mass index at seven years: A pooled analysis of three European birth cohorts Environ Int, 94(#issue#), 399-407 | Intervention/exposure vs comparator
255 | Jabakhanji, S. B.,Boland, F.,Ward, M.,Biesma, R. (2018). Body Mass Index Changes in Early Childhood J Pediatr, 202(#issue#), 106-114 | Outcome
256 | Jackson, D. B. (2016). Breastfeeding duration and offspring conduct problems: The moderating role of genetic risk Soc Sci Med, 166(#issue#), 128-136 | Outcome
257 | Jackson, D. B.,Beaver, K. M. (2016). The Association Between Breastfeeding Exposure and Duration, Neuropsychological Deficits, and Psychopathic Personality Traits in Offspring: The Moderating Role of 5HTTLPR Psychiatr Q, 87(1), 107-27 | Outcome
258 | Jansson, L. M.,Jordan, C. J.,Velez, M. L. (2018). Perinatal Marijuana Use and the Developing Child Jama, 320(6), 545-546 | Publication status
259 | Jardi, C.,Aranda, N.,Bedmar, C.,Arija, V. (2019). Excess nutritional risk in infants and toddlers in a Spanish city Int J Vitam Nutr Res, #volume#(#issue#), 1-11 | Study design
260 | Jardi, C.,Hernandez-Martinez, C.,Canals, J.,Arija, V.,Bedmar, C.,Voltas, N.,Aranda, N. (2018). Influence of breastfeeding and iron status on mental and psychomotor development during the first year of life Infant Behav Dev, 50(#issue#), 300-310 | Intervention/exposure vs comparator
261 | Jarvinen, K. M. (2018). Variations in Human Milk Composition: Impact on Immune Development and Allergic Disease Susceptibility Breastfeed Med, 13(S1), S11-s13 | Study design
262 | Jess, T.,Morgen, C. S.,Harpsoe, M. C.,Sorensen, T. I. A.,Ajslev, T. A.,Antvorskov, J. C.,Allin, K. H. (2019). Antibiotic use during pregnancy and childhood overweight: A population-based nationwide cohort study Sci Rep, 9(1), 11528 | Intervention/exposure vs comparator
263 | Jia, N.,Gu, G.,Zhao, L.,He, S.,Xiong, F.,Chai, Y.,Quan, L.,Hou, H.,Dai, Y. (2018). Longitudinal study of breastfeeding and growth in 0-6 month infants Asia Pac J Clin Nutr, 27(6), 1294-1301 | Intervention/exposure vs comparator
264 | Johansson, E. K.,Bergstrom, A.,Kull, I.,Lind, T.,Soderhall, C.,Melen, E.,Asad, S.,Bradley, M.,Lieden, A.,Ballardini, N.,Wahlgren, C. F. (2018). Prognosis of Preschool Eczema and Factors of Importance for Remission Acta Derm Venereol, 98(7), 630-635 | Outcome
265 | Johansson, U.,Öhlund, I.,Hernell, O.,Lönnerdal, B.,Lindberg, L.,Lind, T. (2019). Protein-reduced complementary foods based on nordic ingredients combined with systematic introduction of taste portions increase intake of fruits and vegetables in 9 month old infants: A randomised controlled trial Nutrients, 11(6), #Pages# | Intervention/exposure vs comparator
266 | Jones, A. (2016). INTERGENERATIONAL EDUCATIONAL ATTAINMENT, FAMILY CHARACTERISTICS AND CHILD OBESITY J Biosoc Sci, 48(4), 557-76 | Study design
267 | Jonsson, K.,Barman, M.,Brekke, H. K.,Hesselmar, B.,Johansen, S.,Sandberg, A. S.,Wold, A. E. (2017). Late introduction of fish and eggs is associated with increased risk of allergy development - results from the FARMFLORA birth cohort Food Nutr Res, 61(1), 1393306 | Outcome
268 | Jonsson, K.,Barman, M.,Moberg, S.,Sjoberg, A.,Brekke, H. K.,Hesselmar, B.,Sandberg, A. S.,Wold, A. E. (2016). Serum fatty acids in infants, reflecting family fish consumption, were inversely associated with allergy development but not related to farm residence Acta Paediatr, 105(12), 1462-1471 | Outcome
269 | Joo, E. Y.,Kim, K. Y.,Kim, D. H.,Lee, J. E.,Kim, S. K. (2016). Iron deficiency anemia in infants and toddlers Blood Res, 51(4), 268-273 | Intervention/exposure vs comparator, Participant health
270 | Jose, Am- L.,Federico, L. V.,Gil-Campos, M.,Maldonado, J.,Flores, K.,Benavides, R.,Jaldo, R.,Jimenez, I.,Fonolla, J.,Olivares, M. (2016). Consumption of the human milk strain bifidobacterium breve cect7263 might improve symptoms of infant colic Journal of clinical gastroenterology, 50(#issue#), S226- | Study design
271 | Kain, J.,Leyton, B.,Baur, L.,Lira, M.,Corvalán, C. (2019). Demographic, social and health-related variables that predict normal-weight preschool children having overweight or obesity when entering primary education in Chile Nutrients, 11(6), #Pages# | Confounders, Intervention/exposure vs comparator
272 | Kajzer, J.,Oliver, J.,Marriage, B. (2016). Gastrointestinal tolerance of formula supplemented with oligosaccharides FASEB journal. Conference: experimental biology 2016, EB. San diego, CA united states. Conference start: 20160402. Conference end: 20160406. Conference publication: (var.pagings), 30(no pagination), #Pages# | Publication status
273 | Kalhoff, H.,Kersting, M. (2016). Adequate iron supply in infants fed according to dietary guidelines? Journal of pediatric gastroenterology and nutrition, 62(#issue#), 873- | Publication status
274 | Kalhoff, Hermann,Kersting, Mathilde (2017). Breastfeeding or formula feeding and iron status in the second 6 months of life: A critical role for complementary feeding #journal#, 187(#issue#), 333-333 | Publication status
275 | Kampouri, M.,Kyriklaki, A.,Roumeliotaki, T.,Koutra, K.,Anousaki, D.,Sarri, K.,Vassilaki, M.,Kogevinas, M.,Chatzi, L. (2018). Patterns of Early-Life Social and Environmental Exposures and Child Cognitive Development, Rhea Birth Cohort, Crete, Greece Child Dev, 89(4), 1063-1073 | Outcome
276 | Kanazawa, S.,Segal, N. L. (2017). Same-sex twins are taller and heavier than opposite-sex twins (but only if breastfed): Possible evidence for sex bias in human breast milk J Exp Child Psychol, 156(#issue#), 186-191 | Outcome
277 | Kapoor, M.,Bird, J. A. (2017). Cow’s milk protein is often tolerated by children with oat-induced FPIES Journal of Allergy and Clinical Immunology: In Practice, 5(2), 496-497 | Outcome
278 | Katsuragi, S.,Okamura, T.,Kokubo, Y.,Watanabe, M.,Higashiyama, A.,Ikeda, T.,Miyamoto, Y. (2019). The Perinatal Condition Around Birth and Cardiovascular Risk Factors in the Japanese General Population: The Suita Study Journal of atherosclerosis and thrombosis, #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
279 | Kaul, P.,Bowker, S. L.,Savu, A.,Yeung, R. O.,Donovan, L. E.,Ryan, E. A. (2019). Association between maternal diabetes, being large for gestational age and breast-feeding on being overweight or obese in childhood Diabetologia, 62(2), 249-258 | Intervention/exposure vs comparator
280 | Kawai, E.,Takagai, S.,Takei, N.,Itoh, H.,Kanayama, N.,Tsuchiya, K. J. (2017). Maternal postpartum depressive symptoms predict delay in non-verbal communication in 14-month-old infants Infant Behav Dev, 46(#issue#), 33-45 | Outcome
281 | Kelly, E.,DunnGalvin, G.,Murphy, B. P.,O’B Hourihane J (2019). Formula supplementation remains a risk for cow’s milk allergy in breast-fed infants Pediatr Allergy Immunol, #volume#(#issue#), #Pages# | Study design
282 | Kerr, J. A.,Long, C.,Clifford, S. A.,Muller, J.,Gillespie, A. N.,Donath, S.,Wake, M. (2017). Early-life exposures predicting onset and resol of childhood overweight or obesity Archives of Disease in Childhood, 102(10), 922-929 | Outcome
283 | Kerr, J. A.,Long, C.,Clifford, S. A.,Muller, J.,Gillespie, A. N.,Donath, S.,Wake, M. (2017). Early-life exposures predicting onset and resolution of childhood overweight or obesity Arch Dis Child, 102(10), 915-922 | Outcome
284 | Kesztyüs, D.,Traub, M.,Lauer, R.,Kesztyüs, T.,Steinacker, J. M. (2016). Correlates of longitudinal changes in the waist-to-height ratio of primary school children: Implications for prevention Preventive Medicine Reports, 3(#issue#), 1-6 | Outcome
285 | Khatiwada, A.,Shoaibi, A.,Neelon, B.,Emond, J. A.,Benjamin-Neelon, S. E. (2018). Household chaos during infancy and infant weight status at 12 months Pediatr Obes, 13(10), 607-613 | Intervention/exposure vs comparator, Outcome
286 | Khatun, M.,Al Mamun, A.,Scott, J.,William, G. M.,Clavarino, A.,Najman, J. M. (2017). Do children born to teenage parents have lower adult intelligence? A prospective birth cohort study PLoS One, 12(3), e0167395 | Outcome
287 | Khodabakhshi, A.,Mehrad-Majd, H.,Vahid, F.,Safarian, M. (2018). Association of maternal breast milk and serum levels of macronutrients, hormones, and maternal body composition with infant’s body weight Eur J Clin Nutr, 72(3), 394-400 | Intervention/exposure vs comparator
288 | Kim, H.,Kim, H.,Lee, E.,Kim, Y.,Ha, E. H.,Chang, N. (2017). Association between maternal intake of n-6 to n-3 fatty acid ratio during pregnancy and infant neurodevelopment at 6 months of age: results of the MOCEH cohort study Nutr J, 16(1), 23 | Intervention/exposure vs comparator
289 | Kim, Y. H.,Kim, K. W.,Lee, S. Y.,Koo, K. O.,Kwon, S. O.,Seo, J. H.,Suh, D. I.,Shin, Y. H.,Ahn, K.,Oh, S. Y.,Lee, S.,Sohn, M. H.,Hong, S. J. (2019). Maternal Perinatal Dietary Patterns Affect Food Allergy Development in Susceptible Infants J Allergy Clin Immunol Pract, #volume#(#issue#), #Pages# | Outcome
290 | Kimura, Masahiko,Kurozawa, Youichi,Saito, Yumi,Watanabe, Hiroshi,Kobayashi, Ayame,Taketani, Takeshi (2018). High prevalence of anemia in 10-month-old breast-fed Japanese infants Pediatrics International, 60(7), 651-655 | Study design
291 | Kirchberg, F. F.,Hellmuth, C.,Totzauer, M.,Uhl, O.,Closa-Monasterolo, R.,Escribano, J.,Gruszfeld, D.,Gradowska, K.,Verduci, E.,Mariani, B.,Moretti, M.,Rousseaux, D.,Koletzko, B. (2019). Impact of infant protein supply and other early life factors on plasma metabolome at 5.5 and 8 years of age: a randomized trial Int J Obes (Lond), #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
292 | Kishi, R.,Araki, A.,Minatoya, M.,Hanaoka, T.,Miyashita, C.,Itoh, S.,Kobayashi, S.,Ait Bamai, Y.,Yamazaki, K.,Miura, R.,Tamura, N.,Ito, K.,Goudarzi, H. (2017). The Hokkaido Birth Cohort Study on Environment and Children’s Health: cohort profile-updated 2017 Environ Health Prev Med, 22(1), 46 | Intervention/exposure vs comparator
293 | Kjaer, T. W.,Faurholt-Jepsen, D.,Medrano, R.,Elwan, D.,Mehta, K.,Christensen, V. B.,Wojcicki, J. M. (2019). Higher Birthweight and Maternal Pre-pregnancy BMI Persist with Obesity Association at Age 9 in High Risk Latino Children J Immigr Minor Health, 21(1), 89-97 | Intervention/exposure vs comparator
294 | Kjellberg, E.,Roswall, J.,Bergman, S.,Strandvik, B.,Dahlgren, J. (2018). Serum n-6 and n-9 Fatty Acids Correlate With Serum IGF-1 and Growth Up to 4 Months of Age in Healthy Infants J Pediatr Gastroenterol Nutr, 66(1), 141-146 | Intervention/exposure vs comparator
295 | Klingberg, S.,Brekke, H. K.,Ludvigsson, J. (2019). Introduction of fish and other foods during infancy and risk of asthma in the All Babies In Southeast Sweden cohort study Eur J Pediatr, 178(3), 395-402 | Outcome
296 | Klopp, A.,Vehling, L.,Becker, A. B.,Subbarao, P.,Mandhane, P. J.,Turvey, S. E.,Lefebvre, D. L.,Sears, M. R.,Azad, M. B. (2017). Modes of Infant Feeding and the Risk of Childhood Asthma: A Prospective Birth Cohort Study J Pediatr, 190(#issue#), 192-199.e2 | Outcome
297 | Knip, M.,Akerblom, H. K.,Al Taji, E.,Becker, D.,Bruining, J.,Castano, L.,Danne, T.,de Beaufort, C.,Dosch, H. M.,Dupre, J.,Fraser, W. D.,Howard, N.,Ilonen, J.,Konrad, D.,Kordonouri, O.,Krischer, J. P.,Lawson, M. L.,Ludvigsson, J.,Madacsy, L.,Mahon, J. L.,Ormisson, A.,Palmer, J. P.,Pozzilli, P.,Savilahti, E.,Serrano-Rios, M.,Songini, M.,Taback, S.,Vaarala, O.,White, N. H.,Virtanen, S. M.,Wasikowa, R. (2018). Effect of Hydrolyzed Infant Formula vs Conventional Formula on Risk of Type 1 Diabetes: The TRIGR Randomized Clinical Trial Jama, 319(1), 38-48 | Intervention/exposure vs comparator
298 | Koh, K. (2017). Maternal breastfeeding and children’s cognitive development Soc Sci Med, 187(#issue#), 101-108 | Study design, Intervention/exposure vs comparator
299 | Korpela, K.,Salonen, A.,Virta, L. J.,Kekkonen, R. A.,de Vos, W. M. (2016). Association of Early-Life Antibiotic Use and Protective Effects of Breastfeeding: Role of the Intestinal Microbiota JAMA Pediatr, 170(8), 750-7 | Study design
300 | Kouwenhoven, S.,Antl, N.,Finken, M.,Van Der Beek, E.,Koletzko, B.,Van Goudoever, J. (2018). Safety of a modified, low protein infant formula in term infants; An RCT with a reference breastfed group Journal of pediatric gastroenterology and nutrition, 66(#issue#), 915-916 | Publication status
301 | Kramer, M. S.,Davies, N.,Oken, E.,Martin, R. M.,Dahhou, M.,Zhang, X.,Yang, S. (2018). Infant feeding and growth: putting the horse before the cart Am J Clin Nutr, 107(4), 635-639 | Outcome
302 | Kuniyoshi, Y.,Kikuya, M.,Matsubara, H.,Ishikuro, M.,Obara, T.,Kure, S.,Kuriyama, S. (2019). Association of Feeding Practice with Childhood Overweight and/or Obesity in Affected Areas Before and After the Great East Japan Earthquake Breastfeed Med, 14(6), 382-389 | Intervention/exposure vs comparator
303 | Kwok, M. K.,Schooling, C. M.,Subramanian, S. V.,Leung, G. M.,Kawachi, I. (2016). Pathways from parental educational attainment to adolescent blood pressure J Hypertens, 34(9), 1787-95 | Intervention/exposure vs comparator
304 | Lakshman, Rajalakshmi,Clifton, Emma A.,Ong, Ken K. (2017). Baby-Led Weaning--Safe and Effective but Not Preventive of Obesity JAMA Pediatrics, 171(9), 832-833 | Publication status
305 | Lambidou, M.,Alteheld, B.,Jochum, F.,Nomayo, A.,Stehle, P. (2016). Effect of high beta-palmitate infant formula supplemented with galacto-oligosaccharides on stool fatty acid soaps Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 879 | Publication status Outcome
306 | Larnkjaer, A.,Ong, K. K.,Carlsen, E. M.,Ejlerskov, K. T.,Molgaard, C.,Michaelsen, K. F. (2018). The Influence of Maternal Obesity and Breastfeeding on Infant Appetite- and Growth-Related Hormone Concentrations: The SKOT Cohort Studies Horm Res Paediatr, 90(1), 28-38 | Intervention/exposure vs comparator
307 | Larsson, M. W.,Lind, M. V.,Larnkjaer, A.,Due, A. P.,Blom, I. C.,Wells, J.,Lai, C. T.,Molgaard, C.,Geddes, D. T.,Michaelsen, K. F. (2018). Excessive Weight Gain Followed by Catch-Down in Exclusively Breastfed Infants: An Exploratory Study Nutrients, 10(9), #Pages# | Intervention/exposure vs comparator
308 | Lauritzen, L.,Amundsen, I. D.,Damsgaard, C. T.,Lind, M. V.,Schnurr, T. M.,Hansen, T.,Michaelsen, K. F.,Vogel, U. (2019). FADS and PPARG2 Single Nucleotide Polymorphisms are Associated with Plasma Lipids in 9-Mo-Old Infants J Nutr, 149(5), 708-715 | Study design
309 | Lauritzen, L.,Eriksen, S. E.,Hjorth, M. F.,Nielsen, M. S.,Olsen, S. F.,Stark, K. D.,Michaelsen, K. F.,Damsgaard, C. T. (2016). Maternal fish oil supplementation during lactation is associated with reduced height at 13 years of age and higher blood pressure in boys only British Journal of Nutrition, 116(12), 2082-2090 | Intervention/exposure vs comparator
310 | Laws, R. A.,Denney-Wilson, E. A.,Taki, S.,Russell, C. G.,Zheng, M.,Litterbach, E. K.,Ong, K. L.,Lymer, S. J.,Elliott, R.,Campbell, K. J. (2018). Key Lessons and Impact of the Growing Healthy mHealth Program on Milk Feeding, Timing of Introduction of Solids, and Infant Growth: Quasi-Experimental Study JMIR Mhealth Uhealth, 6(4), e78 | Intervention/exposure vs comparator
311 | Laws, Rachel,Litterbach, Eloise-Kate,Taki, Sarah,Russell, Georgina,Denney-Wilson, Elizabeth,Campbell, Karen (2019). Obesity prevention in infants: A qualitative study exploring the influence of the Growing healthy program on infant feeding behaviours Obesity Research & Clinical Practice, 13(1), 92-92 | Publication status
312 | Lee, H. R.,Shin, S.,Yoon, J. H.,Roh, E. Y.,Chang, J. Y. (2016). Reference Intervals of Hematology and Clinical Chemistry Analytes for 1-Year-Old Korean Children Ann Lab Med, 36(5), 481-8 | Study design
313 | Lee, H.,Park, H.,Ha, E.,Hong, Y. C.,Ha, M.,Park, H.,Kim, B. N.,Lee, B.,Lee, S. J.,Lee, K. Y.,Kim, J. H.,Jeong, K. S.,Kim, Y. (2016). Effect of Breastfeeding Duration on Cognitive Development in Infants: 3-Year Follow-up Study J Korean Med Sci, 31(4), 579-84 | Outcome
314 | Lee, I.,Bang, K. S.,Moon, H.,Kim, J. (2019). Risk Factors for Obesity Among Children Aged 24 to 80 months in Korea: A Decision Tree Analysis J Pediatr Nurs, 46(#issue#), e15-e23 | Intervention/exposure vs comparator
315 | Lee, J. W.,Lee, M.,Lee, J.,Kim, Y. J.,Ha, E.,Kim, H. S. (2019). The Protective Effect of Exclusive Breastfeeding on Overweight/Obesity in Children with High Birth Weight J Korean Med Sci, 34(10), e85 | Outcome
316 | Lee, M. T.,Wu, C. C.,Ou, C. Y.,Chang, J. C.,Liu, C. A.,Wang, C. L.,Chuang, H.,Kuo, H. C.,Hsu, T. Y.,Chen, C. P.,Yang, K. D. (2017). A prospective birth cohort study of different risk factors for development of allergic diseases in offspring of non-atopic parents Oncotarget, 8(7), 10858-10870 | Outcome
317 | Lee, M.,Ha, M.,Hong, Y. C.,Park, H.,Kim, Y.,Kim, E. J.,Kim, Y.,Ha, E. (2019). Exposure to prenatal secondhand smoke and early neurodevelopment: Mothers and Children’s Environmental Health (MOCEH) study Environ Health, 18(1), 22 | Intervention/exposure vs comparator
318 | Lee, S. H.,Weerasinghe, Wmsp,van der Werf, J. H. J. (2017). Genotype-environment interaction on human cognitive function conditioned on the status of breastfeeding and maternal smoking around birth Sci Rep, 7(1), 6087 | Outcome
319 | Lee, Y. A.,Cho, S. W.,Sung, H. K.,Kim, K.,Song, Y. S.,Moon, S. J.,Oh, J. W.,Ju, D. L.,Choi, S.,Song, S. H.,Cheon, G. J.,Park, Y. J.,Shin, C. H.,Park, S. K.,Jun, J. K.,Chung, J. K. (2018). Effects of Maternal Iodine Status during Pregnancy and Lactation on Maternal Thyroid Function and Offspring Growth and Development: A Prospective Study Protocol for the Ideal Breast Milk Cohort Endocrinol Metab (Seoul), 33(3), 395-402 | Study design, Intervention/exposure vs comparator
320 | Lee-Sarwar, K. A.,Kelly, R. S.,Lasky-Su, J.,Zeiger, R. S.,O’Connor, G. T.,Sandel, M. T.,Bacharier, L. B.,Beigelman, A.,Laranjo, N.,Gold, D. R.,Weiss, S. T.,Litonjua, A. A. (2019). Integrative analysis of the intestinal metabolome of childhood asthma J Allergy Clin Immunol, 144(2), 442-454 | Intervention/exposure vs comparator
321 | Lemcke, S.,Parner, E. T.,Bjerrum, M.,Thomsen, P. H.,Lauritsen, M. B. (2016). Early development in children that are later diagnosed with disorders of attention and activity: a longitudinal study in the Danish National Birth Cohort Eur Child Adolesc Psychiatry, 25(10), 1055-66 | Outcome
322 | Lemcke, S.,Parner, E. T.,Bjerrum, M.,Thomsen, P. H.,Lauritsen, M. B. (2018). EARLY REGULATION IN CHILDREN WHO ARE LATER DIAGNOSED WITH AUTISM SPECTRUM DISORDER. A LONGITUDINAL STUDY WITHIN THE DANISH NATIONAL BIRTH COHORT Infant Ment Health J, 39(2), 170-182 | Confounders
323 | Lentferink, Yvette E.,Elst, Marieke A. J.,Knibbe, Catherijne A. J.,van der Vorst, Marja M. J. (2017). Predictors of Insulin Resistance in Children versus Adolescents with Obesity Journal of Obesity, #volume#(#issue#), 1-7 | Intervention/exposure vs comparator
324 | Lepping, R. J.,Honea, R. A.,Martin, L. E.,Liao, K.,Choi, I. Y.,Lee, P.,Papa, V. B.,Brooks, W. M.,Shaddy, D. J.,Carlson, S. E.,Colombo, J.,Gustafson, K. M. (2019). Long-chain polyunsaturated fatty acid supplementation in the first year of life affects brain function, structure, and metabolism at age nine years Dev Psychobiol, 61(1), 5-16 | Intervention/exposure vs comparator
325 | Lertxundi, A.,Andiarena, A.,Martinez, M. D.,Ayerdi, M.,Murcia, M.,Estarlich, M.,Guxens, M.,Sunyer, J.,Julvez, J.,Ibarluzea, J. (2019). Prenatal exposure to PM2.5 and NO2 and sex-dependent infant cognitive and motor development Environ Res, 174(#issue#), 114-121 | Intervention/exposure vs comparator
326 | Leung, J. Y.,Kwok, M. K.,Leung, G. M.,Schooling, C. M. (2016). Breastfeeding and childhood hospitalizations for asthma and other wheezing disorders Ann Epidemiol, 26(1), 21-7.e1-3 | Already included in P/B24 search
327 | Li, Y.,Mu, Z.,Wang, H.,Liu, J.,Jiang, F. (2018). The role of particulate matters on methylation of IFN-gamma and IL-4 promoter genes in pediatric allergic rhinitis Oncotarget, 9(25), 17406-17419 | Outcome
328 | Liao, K.,McCandliss, B. D.,Carlson, S. E.,Colombo, J.,Shaddy, D. J.,Kerling, E. H.,Lepping, R. J.,Sittiprapaporn, W.,Cheatham, C. L.,Gustafson, K. M. (2017). Event-related potential differences in children supplemented with long-chain polyunsaturated fatty acids during infancy Dev Sci, 20(5), #Pages# | Intervention/exposure vs comparator
329 | Libuda, L.,Hilbig, A.,Berber-Al-Tawil, S.,Kalhoff, H.,Kersting, M. (2018). Association between full breastfeeding, timing of complementary food introduction, and iron status in infancy in Germany: results of a secondary analysis of a randomized trial Eur J Nutr, 57(2), 523-531 | Intervention/exposure vs comparator
330 | Lichtman-Sadot, S.,Bell, N. P. (2017). Child Health in Elementary School Following California’s Paid Family Leave Program J Policy Anal Manage, 36(4), 790-827 | Intervention/exposure vs comparator
331 | Lifschitz, C. (2016). Can we do something in early life to reduce the risk of obesity? Iranian journal of neonatology, 7(2), 16-19 | Study design
332 | Lind, Mads V.,Larnkjær, Anni,Mølgaard, Christian,Michaelsen, Kim F. (2017). Early Nutrition and Its Effect on Growth, Body Composition, and Later Obesity World Review of Nutrition & Dietetics, 116(#issue#), 118-133 | Publication status, Study design
333 | Liotto, N.,Orsi, A.,Menis, C.,Piemontese, P.,Morlacchi, L.,Condello, C. C.,Gianni, M. L.,Roggero, P.,Mosca, F. (2018). Clinical evaluation of two different protein content formulas fed to full-term healthy infants: a randomized controlled trial BMC Pediatr, 18(1), 59 | Confounders
334 | Little, C.,Blattner, C. M.,Young, J., 3rd (2017). Update: Can breastfeeding and maternal diet prevent atopic dermatitis? Dermatol Pract Concept, 7(3), 63-65 | Study design
335 | Liu, J. X.,Xu, X.,Liu, J. H.,Hardin, J. W.,Li, R. (2018). Association of maternal gestational weight gain with their offspring’s anthropometric outcomes at late infancy and 6 years old: mediating roles of birth weight and breastfeeding duration Int J Obes (Lond), 42(1), 8-14 | Outcome
336 | Liu, J.,Liu, J.,Frongillo, E. A., Jr.,Boghossian, N. S.,Cai, B.,Zhou, H.,Hazlett, L. J. (2019). Body mass index trajectories during the first year of life and their determining factors Am J Hum Biol, 31(1), e23188 | Outcome
337 | Liu, Q.,Wang, W.,Jing, W. (2019). Indoor air pollution aggravates asthma in Chinese children and induces the changes in serum level of miR-155 Int J Environ Health Res, 29(1), 22-30 | Outcome
338 | Logan, C. A.,Brandt, S.,Wabitsch, M.,Brenner, H.,Wiens, F.,Stahl, B.,Marosvolgyi, T.,Decsi, T.,Rothenbacher, D.,Genuneit, J. (2017). New approach shows no association between maternal milk fatty acid composition and childhood wheeze or asthma Allergy, 72(9), 1374-1383 | Outcome
339 | Logan, C. A.,Weiss, J. M.,Koenig, W.,Stahl, B.,Carr, P. R.,Brenner, H.,Rothenbacher, D.,Genuneit, J. (2019). Soluble CD14 concentration in human breast milk and its potential role in child atopic dermatitis: Results of the Ulm Birth Cohort Studies Clin Exp Allergy, 49(2), 199-206 | Outcome
340 | Lonnerdal, B.,Kvistgaard, A. S.,Peerson, J. M.,Donovan, S. M.,Peng, Y. M. (2016). Growth, Nutrition, and Cytokine Response of Breast-fed Infants and Infants Fed Formula With Added Bovine Osteopontin J Pediatr Gastroenterol Nutr, 62(4), 650-7 | Intervention/exposure vs comparator
341 | Lossius, A. K.,Magnus, M. C.,Lunde, J.,Stordal, K. (2018). Prospective Cohort Study of Breastfeeding and the Risk of Childhood Asthma J Pediatr, 195(#issue#), 182-189.e2 | Outcome
342 | Love, T. M. T.,Thurston, S. W.,Davidson, P. W. (2017). Finding vulnerable subpopulations in the Seychelles Child Development Study: Effect modification with latent groups Statistical Methods in Medical Research, 26(2), 809-822 | Intervention/exposure vs comparator
343 | Luby, J. L.,Belden, A. C.,Whalen, D.,Harms, M. P.,Barch, D. M. (2016). Breastfeeding and Childhood IQ: The Mediating Role of Gray Matter Volume J Am Acad Child Adolesc Psychiatry, 55(5), 367-75 | Outcome
344 | Luecken, L. J.,Jewell, S. L.,MacKinnon, D. P. (2017). Maternal acculturation and the growth of impoverished Mexican American infants Obesity (Silver Spring), 25(2), 445-451 | Intervention/exposure vs comparator
345 | Lund-Blix, N. A.,Dydensborg Sander, S.,Stordal, K.,Nybo Andersen, A. M.,Ronningen, K. S.,Joner, G.,Skrivarhaug, T.,Njolstad, P. R.,Husby, S.,Stene, L. C. (2017). Infant Feeding and Risk of Type 1 Diabetes in Two Large Scandinavian Birth Cohorts Diabetes Care, 40(7), 920-927 | Outcome
346 | Lurbe, E.,Aguilar, F.,Alvarez, J.,Redon, P.,Torro, M. I.,Redon, J. (2018). Determinants of Cardiometabolic Risk Factors in the First Decade of Life: A Longitudinal Study Starting at Birth Hypertension, 71(3), 437-443 | Outcome
347 | M. R, Perkin,K, Logan,A, Tseng (2016). Randomized Trial of Introduction of Allergenic Food in Breast-Fed Infants Journal of Clinical Chiropractic Pediatrics, 15(3), 1331-1332 | Outcome
348 | Mannan, H. (2018). Early Infant Feeding of Formula or Solid Foods and Risk of Childhood Overweight or Obesity in a Socioeconomically Disadvantaged Region of Australia: A Longitudinal Cohort Analysis Int J Environ Res Public Health, 15(8), #Pages# | Intervention/exposure vs comparator
349 | Marell Hesla, H.,Stenius, F.,Järnbert-Pettersson, H.,Alm, J. (2017). Allergy-related disease in relation to early life exposures—the ALADDIN birth cohort Journal of Allergy and Clinical Immunology, 139(2), 686-688 | Publication status
350 | Marques, R. C.,Abreu, L.,Bernardi, J. V.,Dorea, J. G. (2016). Traditional living in the Amazon: Extended breastfeeding, fish consumption, mercury exposure and neurodevelopment Ann Hum Biol, 43(4), 360-70 | Outcome
351 | Martens, P. J.,Shafer, L. A.,Dean, H. J.,Sellers, E. A.,Yamamoto, J.,Ludwig, S.,Heaman, M.,Phillips-Beck, W.,Prior, H. J.,Morris, M.,McGavock, J.,Dart, A. B.,Shen, G. X. (2016). Breastfeeding Initiation Associated With Reduced Incidence of Diabetes in Mothers and Offspring Obstet Gynecol, 128(5), 1095-1104 | Outcome
352 | Martens, Patricia J.,Shafer, Leigh Anne,Dean, Heather,Sellers, Elizabeth,Yamamoto, Jennifer,Ludwig, Sora,Heaman, Maureen,Phillips-Beck, Wanda,Prior, Heather,Morris, Magaret,McGavock, Jonathan,Dart, Allison,Shen, Garry (2016). 53 - Breastfeeding Initiation Associated with Reduced Incidence of Diabetes in Manitoba Canadian Journal of Diabetes, 40(#issue#), S18-S18 | Outcome
353 | Martin, C. R. (2019). Breast Milk Lipidomics: Insights to Infant Health Requirements and Targeted Strategies for the Vulnerable Breastfeed Med, 14(S1), S13-s14 | Study design
354 | Martin, R. M.,Kramer, M. S.,Patel, R.,Rifas-Shiman, S. L.,Thompson, J.,Yang, S.,Vilchuck, K.,Bogdanovich, N.,Hameza, M.,Tilling, K.,Oken, E. (2017). Effects of Promoting Long-term, Exclusive Breastfeeding on Adolescent Adiposity, Blood Pressure, and Growth Trajectories: A Secondary Analysis of a Randomized Clinical Trial JAMA Pediatr, 171(7), e170698 | Outcome
355 | Mascheretti, S.,Trezzi, V.,Giorda, R.,Boivin, M.,Plourde, V.,Vitaro, F.,Brendgen, M.,Dionne, G.,Marino, C. (2017). Complex effects of dyslexia risk factors account for ADHD traits: evidence from two independent samples J Child Psychol Psychiatry, 58(1), 75-82 | Outcome
356 | Massion, S.,Wickham, S.,Pearce, A.,Barr, B.,Law, C.,Taylor-Robinson, D. (2016). Exploring the impact of early life factors on inequalities in risk of overweight in UK children: findings from the UK Millennium Cohort Study Arch Dis Child, 101(8), 724-30 | Outcome
357 | Mastroeni, M. F.,Mastroeni, Ssbs,Czarnobay, S. A.,Ekwaru, J. P.,Loehr, S. A.,Veugelers, P. J. (2017). Breast-feeding duration for the prevention of excess body weight of mother-child pairs concurrently: a 2-year cohort study Public Health Nutr, 20(14), 2537-2548 | Outcome
358 | Matro, R.,Martin, C. F.,Wolf, D.,Shah, S. A.,Mahadevan, U. (2018). Exposure Concentrations of Infants Breastfed by Women Receiving Biologic Therapies for Inflammatory Bowel Diseases and Effects of Breastfeeding on Infections and Development Gastroenterology, 155(3), 696-704 | Confounders, Intervention/exposure vs comparator
359 | McCallister, M.,Medrano, R.,Wojcicki, J. (2018). Early life obesity increases the risk for asthma in San Francisco born Latina girls Allergy Asthma Proc, 39(4), 273-280 | Intervention/exposure vs comparator
360 | McCarthy, E. K.,ní Chaoimh, C.,Hourihane, J. O. B.,Kenny, L. C.,Irvine, A. D.,Murray, D. M.,Kiely, M. (2017). Iron intakes and status of 2-year-old children in the Cork BASELINE Birth Cohort Study Maternal and Child Nutrition, 13(3), #Pages# | Study design, Intervention/exposure vs comparator
361 | McIntyre, L. M.,Griffen, A. M.,BrintzenhofeSzoc, K. (2018). Breast Is Best … Except When It’s Not J Hum Lact, 34(3), 575-580 | Study design
362 | McKinlay, C.,Okesene-Gafa, K.,Taylor, R.,Wall, C.,Rush, E.,McCowan, M.,Thompson, J.,Crowther, C.,McCowan, L. (2019). Dietary intervention and/or probiotic capsules in obese pregnant women and infant growth and feeding at 5 months: healthy mums and babies (humba) trial Journal of paediatrics and child health, 55(#issue#), 35- | Publication status
363 | McLeod, G. F.,Fergusson, D. M.,Horwood, L. J.,Boden, J. M.,Carter, F. A. (2018). Childhood predictors of adult adiposity: findings from a longitudinal study N Z Med J, 131(1472), 10-20 | Intervention/exposure vs comparator
364 | Mennella, J. A.,Inamdar, L.,Pressman, N.,Schall, J. I.,Papas, M. A.,Schoeller, D.,Stallings, V. A.,Trabulsi, J. C. (2018). Type of infant formula increases early weight gain and impacts energy balance: a randomized controlled trial Am J Clin Nutr, 108(5), 1015-1025 | Intervention/exposure vs comparator
365 | Mennella, J. A.,Trabulsi, J. C.,Papas, M. A. (2016). Effects of cow milk versus extensive protein hydrolysate formulas on infant cognitive development Amino Acids, 48(3), 697-705 | Intervention/exposure vs comparator
366 | Meyer, D. M.,Brei, C.,Stecher, L.,Much, D.,Brunner, S.,Hauner, H. (2019). Associations between long-chain PUFAs in maternal blood, cord blood, and breast milk and offspring body composition up to 5 years: follow-up from the INFAT study Eur J Clin Nutr, 73(3), 458-464 | Intervention/exposure vs comparator
367 | Michael, N.,Gupta, V.,Sadananthan, S. A.,Sampathkumar, A.,Chen, L.,Pan, H.,Tint, M. T.,Lee, K. J.,Loy, S. L.,Aris, I. M.,Shek, L. P.,Yap, F. K. P.,Godfrey, K. M.,Leow, M. K.,Lee, Y. S.,Kramer, M. S.,Henry, C. J.,Fortier, M. V.,Seng Chong, Y.,Gluckman, P. D.,Karnani, N.,Velan, S. S. (2019). Determinants of intramyocellular lipid accumulation in early childhood Int J Obes (Lond), #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
368 | Michaliszyn, S. F.,Sjaarda, L. A.,Scifres, C.,Simhan, H.,Arslanian, S. A. (2017). Maternal excess gestational weight gain and infant waist circumference: a 2-y observational study Pediatr Res, 81(1-1), 63-67 | Confounders, Intervention/exposure vs comparator
369 | Michaliszyn, Sara F.,Sjaarda, Lindsey A.,Scifres, Christina,Simhan, Hyagriv,Arslanian, Silva A. (2016). Maternal excess gestational weight gain and infant waist circumference: a 2-y observational study Pediatric Research, #volume#(#issue#), N.PAG-N.PAG | Intervention/exposure vs comparator
370 | Michels, K. A.,Ghassabian, A.,Mumford, S. L.,Sundaram, R.,Bell, E. M. (2018). Breastfeeding and motor development in term and preterm infants in a longitudinal US cohort Journal of Clinical Chiropractic Pediatrics, 17(2), 1467-1467 | Intervention/exposure vs comparator
371 | Michels, K. A.,Ghassabian, A.,Mumford, S. L.,Sundaram, R.,Bell, E. M.,Bello, S. C.,Yeung, E. H. (2017). Breastfeeding and motor development in term and preterm infants in a longitudinal US cohort Am J Clin Nutr, 106(6), 1456-1462 | Intervention/exposure vs comparator
372 | Michie, C. (2016). How to reduce the risks associated with Vitamin D self-supplementation Clinical Pharmacist, 8(5), #Pages# | Publication status
373 | Mihalopoulos, N. L.,Urban, B. M.,Metos, J. M.,Balch, A. H.,Young, P. C.,Jordan, K. C. (2017). Breast-feeding, Leptin:Adiponectin Ratio, and Metabolic Dysfunction in Adolescents with Obesity South Med J, 110(5), 347-352 | Study design, Participant health
374 | Miklavcic, J. J.,Larsen, B. M.,Mazurak, V. C.,Scalabrin, D. M.,MacDonald, I. M.,Shoemaker, G. K.,Casey, L.,Van Aerde, J. E.,Clandinin, M. T. (2017). Reduction of Arachidonate Is Associated With Increase in B-Cell Activation Marker in Infants: A Randomized Trial J Pediatr Gastroenterol Nutr, 64(3), 446-453 | Intervention/exposure vs comparator
375 | Minchin, M. (2016). Still LEAPing to wrong conclusions? Breastfeed Rev, 24(2), 7-10 | Outcome
376 | Modrek, S.,Basu, S.,Harding, M.,White, J. S.,Bartick, M. C.,Rodriguez, E.,Rosenberg, K. D. (2017). Does breastfeeding duration decrease child obesity? An instrumental variables analysis Pediatr Obes, 12(4), 304-311 | Outcome
377 | Mohamad, M.,Loy, S. L.,Lim, P. Y.,Wang, Y.,Soo, K. L.,Mohamed, H. J. J. (2018). Maternal Serum and Breast Milk Adiponectin: The Association with Infant Adiposity Development Int J Environ Res Public Health, 15(6), #Pages# | Intervention/exposure vs comparator
378 | Moore, Alison (2019). The role of breastmilk in body composition World of Irish Nursing & Midwifery, 27(5), 59-59 | Publication status
379 | Moore, B. F.,Sauder, K. A.,Starling, A. P.,Ringham, B. M.,Glueck, D. H.,Dabelea, D. (2017). Exposure to secondhand smoke, exclusive breastfeeding and infant adiposity at age 5 months in the Healthy Start study Pediatr Obes, 12 Suppl 1(#issue#), 111-119 | Study design, Intervention/exposure vs comparator
380 | Morgen, C. S.,Angquist, L.,Baker, J. L.,Andersen, A. N.,Sorensen, T. I. A.,Michaelsen, K. F. (2018). Breastfeeding and complementary feeding in relation to body mass index and overweight at ages 7 and 11 y: a path analysis within the Danish National Birth Cohort Am J Clin Nutr, 107(3), 313-322 | Outcome
381 | Morris, Alan (2018). Risk factors: Breastfeeding reduces risk of type 2 diabetes mellitus Nature Reviews Endocrinology, 14(3), 128-128 | Study design
382 | Moschonis, G.,de Lauzon-Guillain, B.,Jones, L.,Oliveira, A.,Lambrinou, C. P.,Damianidi, L.,Lioret, S.,Moreira, P.,Lopes, C.,Emmett, P.,Charles, M. A.,Manios, Y. (2017). The effect of early feeding practices on growth indices and obesity at preschool children from four European countries and UK schoolchildren and adolescents Eur J Pediatr, 176(9), 1181-1192 | Outcome
383 | Mukherjee, N.,Sutter, T. R.,Arshad, S. H.,Holloway, J. W.,Zhang, H.,Karmaus, W. (2018). Breastfeeding duration modifies the effect of smoking during pregnancy on eczema from early childhood to adolescence Clinical and Experimental Allergy, 48(12), 1688-1697 | Outcome
384 | Munhoz, T. N.,Santos, I. S.,Karam, S. M.,Martines, J.,Pelto, G.,Barcelos, R.,Goncalves, H.,Valle, N. C.,Anselmi, L.,Matijasevich, A. (2017). Effect of childhood nutrition counselling on intelligence in adolescence: a 15-year follow-up of a cluster-randomised trial Public Health Nutr, 20(11), 2034-2041 | Outcome
385 | Musaad, S. M.,Donovan, S. M.,Fiese, B. H. (2016). The Independent and Cumulative Effect of Early Life Risk Factors on Child Growth: A Preliminary Report Child Obes, 12(3), 193-201 | Intervention/exposure vs comparator
386 | Naik, P.,Faridi, M. M. A.,Batra, P.,Madhu, S. V. (2017). Oral Supplementation of Parturient Mothers with Vitamin D and Its Effect on 25OHD Status of Exclusively Breastfed Infants at 6 Months of Age: A Double-Blind Randomized Placebo Controlled Trial Breastfeed Med, 12(10), 621-628 | Country
387 | Nakano, S.,Suzuki, M.,Minowa, K.,Hirai, S.,Takubo, N.,Sakamoto, Y.,Ishijima, M.,Hoshino, E.,Tokita, A.,Shimizu, T. (2018). Current Vitamin D Status in Healthy Japanese Infants and Young Children J Nutr Sci Vitaminol (Tokyo), 64(2), 99-105 | Study design
388 | Nascimento, Jxpt,Ribeiro, C. C. C.,Batista, R. F. L.,de Britto Alves, Mtss,Simoes, V. M. F.,Padilha, L. L.,Cardoso, V. C.,Vianna, E. O.,Bettiol, H.,Barbieri, M. A.,Silva, Aamd (2017). The First 1000 Days of Life Factors Associated with “Childhood Asthma Symptoms”: Brisa Cohort, Brazil Sci Rep, 7(1), 16028 | Outcome
389 | Navarrete, M. A.,Silva, J. R.,Van Ijzendoorn, M. H.,Carcamo, R. A. (2018). Physical and psychosocial development of Mapuche and nonindigenous Chilean toddlers: A modest role of ethnicity Dev Psychopathol, 30(5), 1959-1976 | Outcome
390 | Nazeri, P. (2018). Lactating mothers and infants residing in an area with effective salt iodization program have no need for iodine supplements: results from a doubleblind, placebo-controlled, randomized clinical trial Breastfeeding medicine. Conference: 19th international society for research in human milk and lactation conference, ISRHML 2018. Japan, 13(7), A12-A13 | Intervention/exposure vs comparator
391 | Nazeri, P.,Mirmiran, P.,Tahmasebinejad, Z.,Hedayati, M.,Delshad, H.,Azizi, F. (2017). The Effects of Iodine Fortified Milk on the Iodine Status of Lactating Mothers and Infants in an Area with a Successful Salt Iodization Program: A Randomized Controlled Trial Nutrients, 9(2), #Pages# | Intervention/exposure vs comparator
392 | Nazeri, P.,Tahmasebinejad, Z.,Mehrabi, Y.,Hedayati, M.,Mirmiran, P.,Azizi, F. (2018). Lactating Mothers and Infants Residing in an Area with an Effective Salt Iodization Program Have No Need for Iodine Supplements: Results from a Double-Blind, Placebo-Controlled, Randomized Controlled Trial Thyroid, 28(11), 1547-1558 | Intervention/exposure vs comparator
393 | Newman, K.,O’Donovan, K.,Bear, N.,Robertson, A.,Mutch, R.,Cherian, S. (2019). Nutritional assessment of resettled paediatric refugees in Western Australia J Paediatr Child Health, 55(5), 574-581 | Study design
394 | Niinisto, S.,Takkinen, H. M.,Erlund, I.,Ahonen, S.,Toppari, J.,Ilonen, J.,Veijola, R.,Knip, M.,Vaarala, O.,Virtanen, S. M. (2017). Fatty acid status in infancy is associated with the risk of type 1 diabetes-associated autoimmunity Diabetologia, 60(7), 1223-1233 | Intervention/exposure vs comparator
395 | Nobre, L. N.,Lessa, A. D. (2016). Influence of breastfeeding in the first months of life on blood pressure levels of preschool children J Pediatr (Rio J), 92(6), 588-594 | Outcome
396 | Norman, M. (2017). Breastfeeding and outcome Acta Paediatrica, International Journal of Paediatrics, 106(3), 516 | Publication status
397 | Nowicki, S.,Gregory, S.,Iles-Caven, Y.,Ellis, G.,Golding, J. (2018). Early Home-Life Antecedents of Children’s Locus of Control Front Psychol, 9(#issue#), 2032 | Outcome
398 | Odar Stough, C.,Bolling, C.,Zion, C.,Stark, L. J. (2018). Comparison of High and Normal Birth Weight Infants on Eating, Feeding Practices, and Subsequent Weight Matern Child Health J, 22(12), 1805-1814 | Intervention/exposure vs comparator
399 | O’Donovan, S. M.,O’B Hourihane J,Murray, D. M.,Kenny, L. C.,Khashan, A. S.,Chaoimh, C. N.,Irvine, A. D.,Kiely, M. (2016). Neonatal adiposity increases the risk of atopic dermatitis during the first year of life J Allergy Clin Immunol, 137(1), 108-117 | Outcome
400 | Ohlendorf, J. M.,Robinson, K.,Garnier-Villarreal, M. (2019). The impact of maternal BMI, gestational weight gain, and breastfeeding on early childhood weight: Analysis of a statewide WIC dataset Prev Med, 118(#issue#), 210-215 | Study design, Intervention/exposure vs comparator
401 | Olaya, G. A.,Lawson, M.,Fewtrell, M. (2017). Iron Status at Age 6 Months in Colombian Infants Exclusively Breast-fed for 4 to 5 Versus 6 Months J Pediatr Gastroenterol Nutr, 64(3), 465-471 | Intervention/exposure vs comparator
402 | Olaya, G.,Buitrago, M. F.,Fewtrell, M. (2018). Randomised trial testing new complementary feeding guidelines: effects on food consumption and growth at 6 years of age Journal of pediatric gastroenterology and nutrition, 66(#issue#), 1160- | Publication status
403 | Olson, J. S.,Hayward, M. D. (2017). Breastfeeding, overweight status, and inflammation Soc Sci Res, 64(#issue#), 226-236 | Intervention/exposure vs comparator, Outcome
404 | Oppenheimer, J. J.,Marshall, G. D. (2017). Increasing our knowledge base of asthma Annals of Allergy, Asthma and Immunology, 119(6), 476-479 | Publication status
405 | Orengul, A. C.,Tarakcioglu, M. C.,Gormez, V.,Akkoyun, S.,Zorlu, A.,Aliyeva, N.,Uzuner, S.,Caliskan, Y.,Bikmazer, A. (2019). Duration of Breastfeeding, Bottle-Feeding, and Parafunctional Oral Habits in Relation to Anxiety Disorders Among Children Breastfeed Med, 14(1), 57-62 | Study design
406 | Oropeza-Ceja, L. G.,Rosado, J. L.,Ronquillo, D.,Garcia, O. P.,Caamano, M. D. C.,Garcia-Ugalde, C.,Viveros-Contreras, R.,Duarte-Vazquez, M. A. (2018). Lower Protein Intake Supports Normal Growth of Full-Term Infants Fed Formula: A Randomized Controlled Trial Nutrients, 10(7), #Pages# | Intervention/exposure vs comparator
407 | Ortega-Garcia, J. A.,Kloosterman, N.,Alvarez, L.,Tobarra-Sanchez, E.,Carceles-Alvarez, A.,Pastor-Valero, R.,Lopez-Hernandez, F. A.,Sanchez-Solis, M.,Claudio, L. (2018). Full Breastfeeding and Obesity in Children: A Prospective Study from Birth to 6 Years Child Obes, 14(5), 327-337 | Outcome
408 | Ortelan, N.,Augusto, R. A.,Souza, J. M. P. (2019). Factors associated with the evolution of weight of children in a supplementary feeding program Rev Bras Epidemiol, 22(#issue#), e190002 | Intervention/exposure vs comparator
409 | O’Sullivan, Siobhan (2018). Breastfeeding infants with type 1 diabetes World of Irish Nursing & Midwifery, 26(6), 63-64 | Publication status
410 | Ou, X.,Andres, A.,Pivik, R. T.,Cleves, M. A.,Snow, J. H.,Ding, Z.,Badger, T. M. (2016). Voxel-Based Morphometry and fMRI Revealed Differences in Brain Gray Matter in Breastfed and Milk Formula-Fed Children AJNR Am J Neuroradiol, 37(4), 713-9 | Already excluded from P/B24 search
411 | Owen, C. G.,Oken, E.,Rudnicka, A. R.,Patel, R.,Thompson, J.,Rifas-Shiman, S. L.,Vilchuck, K.,Bogdanovich, N.,Hameza, M.,Kramer, M. S.,Martin, R. M. (2018). The effect of longer-term and exclusive breastfeeding promotion on visual outcome in adolescence Investigative Ophthalmology and Visual Science, 59(7), 2670-2678 | Outcome
412 | Owora, A. H.,Becker, A. B.,Chan-Yeung, M.,Chan, E. S.,Chooniedass, R.,Ramsey, C.,Watson, W. T. A.,Azad, M. B. (2018). Wheeze trajectories are modifiable through early-life intervention and predict asthma in adolescence Pediatr Allergy Immunol, 29(6), 612-621 | Outcome
413 | Ozcan, A.,Kendirci, M.,Kondolot, M.,Kardas, F.,Akin, L. (2017). Evaluation of vitamin D prophylaxis in 3-36-month-old infants and children J Pediatr Endocrinol Metab, 30(5), 543-549 | Study design
414 | Panagiotopoulos, C.,Hadjiyannakis, S.,Henderson, M. (2018). Type 2 Diabetes in Children and Adolescents Canadian Journal of Diabetes, 42(#issue#), S247-S254 | Study design
415 | Pang, W. W.,Tan, P. T.,Cai, S.,Fok, D.,Chua, M. C.,Lim, S. B.,Shek, L. P.,Chan, S. Y.,Tan, K. H.,Yap, F.,Gluckman, P. D.,Godfrey, K. M.,Meaney, M. J.,Broekman, B. F. P.,Kramer, M. S.,Chong, Y. S.,Rifkin-Graboi, A. (2019). Nutrients or nursing? Understanding how breast milk feeding affects child cognition Eur J Nutr, #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
416 | Paolella, Giulia,Vajro, Pietro (2016). Childhood Obesity, Breastfeeding, Intestinal Microbiota, and Early Exposure to Antibiotics JAMA Pediatrics, 170(8), 735-737 | Publication status
417 | Park, A. L.,Tu, K.,Ray, J. G. (2017). Differences in growth of Canadian children compared to the WHO 2006 Child Growth Standards Paediatr Perinat Epidemiol, 31(5), 452-462 | Intervention/exposure vs comparator
418 | Park, S. H.,Ha, E.,Hong, Y. S.,Park, H. (2016). Serum Levels of Persistent Organic Pollutants and Insulin Secretion among Children Age 7-9 Years: A Prospective Cohort Study Environ Health Perspect, 124(12), 1924-1930 | Outcome
419 | Park, S. H.,Ha, E.,Hong, Y. S.,Park, H. (2016). Serum levels of persistent organic pollutants and insulin secretion among children age 7–9 years: A prospective cohort study Environmental Health Perspectives, 124(12), 1924-1930 | Intervention/exposure vs comparator
420 | Park, S. J.,Lee, H. J. (2018). Exclusive breastfeeding and partial breastfeeding reduce the risk of overweight in childhood: A nationwide longitudinal study in Korea Obes Res Clin Pract, 12(2), 222-228 | Intervention/exposure vs comparator
421 | Parkin, P. C.,DeGroot, J.,Maguire, J. L.,Birken, C. S.,Zlotkin, S. (2016). Severe iron-deficiency anaemia and feeding practices in young children Public Health Nutr, 19(4), 716-22 | Study design, Intervention/exposure vs comparator
422 | Parrino, C.,Vinciguerra, F.,La Spina, N.,Romeo, L.,Tumminia, A.,Baratta, R.,Squatrito, S.,Vigneri, R.,Frittitta, L. (2016). Influence of early-life and parental factors on childhood overweight and obesity J Endocrinol Invest, 39(11), 1315-1321 | Study design, Intervention/exposure vs comparator
423 | Patel, N.,Dalrymple, K. V.,Briley, A. L.,Pasupathy, D.,Seed, P. T.,Flynn, A. C.,Poston, L. (2018). Mode of infant feeding, eating behaviour and anthropometry in infants at 6-months of age born to obese women - a secondary analysis of the UPBEAT trial BMC Pregnancy Childbirth, 18(1), 355 | Intervention/exposure vs comparator
424 | Patel, N.,Godfrey, K. M.,Pasupathy, D.,Levin, J.,Flynn, A. C.,Hayes, L.,Briley, A. L.,Bell, R.,Lawlor, D. A.,Oteng-Ntim, E.,Nelson, S. M.,Robson, S. C.,Sattar, N.,Singh, C.,Wardle, J.,White, S. L.,Seed, P. T.,Poston, L. (2017). Infant adiposity following a randomised controlled trial of a behavioural intervention in obese pregnancy International Journal of Obesity, 41(7), 1018-1026 | Intervention/exposure vs comparator
425 | Pattemore, P. K.,Silvers, K. M.,Frampton, C. M.,Wickens, K.,Ingham, T.,Fishwick, D.,Crane, J.,Town, G. I.,Epton, M. J. (2018). Hair nicotine at 15 months old, tobacco exposure and wheeze or asthma from 15 months to 6 years old Pediatr Pulmonol, 53(4), 443-451 | Outcome
426 | Patterson, A. C.,Maditz, K. H.,Harris, C.,Wampler, J.,Kirchoff, A.,Zissman, E.,Berseth, C. L. (2016). Growth and tolerance of a routine infant formula with an alternative DHA source fed to term infants FASEB journal. Conference: experimental biology 2016, EB. San diego, CA united states. Conference start: 20160402. Conference end: 20160406. Conference publication: (var.pagings), 30(no pagination), #Pages# | Publication status
427 | Pattison, K. L.,Kraschnewski, J. L.,Lehman, E.,Savage, J. S.,Downs, D. S.,Leonard, K. S.,Adams, E. L.,Paul, I. M.,Kjerulff, K. H. (2019). Breastfeeding initiation and duration and child health outcomes in the first baby study Prev Med, 118(#issue#), 1-6 | Outcome
428 | Pattison, Krista L.,Kraschnewski, Jennifer L.,Lehman, Erik,Savage, Jennifer S.,Downs, Danielle Symons,Leonard, Krista S.,Adams, Elizabeth L.,Paul, Ian M.,Kjerulff, Kristen H. (2018). Breastfeeding initiation and duration and child health outcomes in the first baby study Preventive Medicine, 115(#issue#), N.PAG-N.PAG | Duplicate
429 | Pauwels, S.,Symons, L.,Vanautgaerden, E. L.,Ghosh, M.,Duca, R. C.,Bekaert, B.,Freson, K.,Huybrechts, I.,Langie, S. A. S.,Koppen, G.,Devlieger, R.,Godderis, L. (2019). The Influence of the Duration of Breastfeeding on the Infant’s Metabolic Epigenome Nutrients, 11(6), #Pages# | Confounders
430 | Pennestri, M. H.,Laganiere, C.,Bouvette-Turcot, A. A.,Pokhvisneva, I.,Steiner, M.,Meaney, M. J.,Gaudreau, H. (2018). Uninterrupted Infant Sleep, Development, and Maternal Mood Pediatrics, 142(6), #Pages# | Intervention/exposure vs comparator
431 | Penny, M. E.,Jimenez, M. M.,Marin, R. M. (2016). Early rapid weight gain and subsequent overweight and obesity in middle childhood in Peru BMC Obes, 3(#issue#), 55 | Outcome
432 | Perez-Gaxiola, G. (2016). Increased bottle size was associated with increased weight gain in infants Arch Dis Child Educ Pract Ed, 101(5), 280 | Study design, Intervention/exposure vs comparator
433 | Perkin, M. R.,Logan, K.,Tseng, A.,Raji, B.,Ayis, S.,Peacock, J.,Brough, H.,Marrs, T.,Radulovic, S.,Craven, J.,Flohr, C.,Lack, G. (2016). Randomized Trial of Introduction of Allergenic Foods in Breast-Fed Infants N Engl J Med, 374(18), 1733-43 | Outcome
434 | Peters, R. L.,Koplin, J. J.,Dharmage, S. C.,Tang, M. L. K.,McWilliam, V. L.,Gurrin, L. C.,Neeland, M. R.,Lowe, A. J.,Ponsonby, A. L.,Allen, K. J. (2019). Early Exposure to Cow’s Milk Protein Is Associated with a Reduced Risk of Cow’s Milk Allergic Outcomes J Allergy Clin Immunol Pract, 7(2), 462-470.e1 | Outcome
435 | Phelan, S.,Hagobian, T. A.,Ventura, A.,Brannen, A.,Erickson-Hatley, K.,Schaffner, A.,Muñoz-Christian, K.,Mercado, A.,Tate, D. F. (2019). ‘Ripple’ effect on infant zBMI trajectory of an internet-based weight loss program for low-income postpartum women Pediatric Obesity, 14(1), N.PAG-N.PAG | Intervention/exposure vs comparator
436 | Philpott, L. (2017). Allergy aware Australian Journal of Pharmacy, 98(1165), 46-50 | Publication status
437 | Pihl, Andreas Friis,Fonvig, Cilius Esmann,Stjernholm, Theresa,Hansen, Torben,Pedersen, Oluf,Holm, Jens-Christian (2016). The Role of the Gut Microbiota in Childhood Obesity Childhood Obesity, 12(4), 292-299 | Study design
438 | Pivik, R. T.,Andres, A.,Bai, S.,Cleves, M. A.,Tennal, K. B.,Gu, Y.,Badger, T. M. (2016). Infant Diet-Related Changes in Syllable Processing Between 4 and 5 Months: Implications for Developing Native Language Sensitivity Dev Neuropsychol, 41(4), 215-230 | Intervention/exposure vs comparator
439 | Pivik, R. T.,Andres, A.,Tennal, K. B.,Gu, Y.,Downs, H.,Bellando, B. J.,Jarratt, K.,Cleves, M. A.,Badger, T. M. (2019). Resting gamma power during the postnatal critical period for GABAergic system development is modulated by infant diet and sex Int J Psychophysiol, 135(#issue#), 73-94 | Intervention/exposure vs comparator
440 | Pluymen, L. P. M.,Dalmeijer, G. W.,Smit, H. A.,Uiterwaal, Cspm,van der Ent, C. K.,van Rossem, L. (2018). Long-chain polyunsaturated fatty acids in infant formula and cardiovascular markers in childhood Matern Child Nutr, 14(2), e12523 | Intervention/exposure vs comparator
441 | Pluymen, L. P. M.,Wijga, A. H.,Gehring, U.,Koppelman, G. H.,Smit, H. A.,van Rossem, L. (2018). Early introduction of complementary foods and childhood overweight in breastfed and formula-fed infants in the Netherlands: the PIAMA birth cohort study Eur J Nutr, 57(5), 1985-1993 | Intervention/exposure vs comparator
442 | Pluymen, L. P. M.,Wijga, A. H.,Gehring, U.,Koppelman, G. H.,Smit, H. A.,van Rossem, L. (2019). Breastfeeding and cardiometabolic markers at age 12: a population-based birth cohort study Int J Obes (Lond), 43(8), 1568-1577 | Outcome
443 | Pluymen, Linda P. M.,Dalmeijer, Geertje W.,Smit, Henriëtte A.,Uiterwaal, Cuno S. P. M.,van Rossem, Lenie,van der Ent, Cornelis K. (2018). Long-chain polyunsaturated fatty acids in infant formula and cardiovascular markers in childhood Maternal & Child Nutrition, 14(2), 1-1 | Intervention/exposure vs comparator
444 | Polidano, C.,Zhu, A.,Bornstein, J. C. (2017). The relation between cesarean birth and child cognitive development Sci Rep, 7(1), 11483 | Intervention/exposure vs comparator
445 | Prpic, I.,Milardovic, A.,Vlasic-Cicvaric, I.,Spiric, Z.,Radic Nisevic, J.,Vukelic, P.,Snoj Tratnik, J.,Mazej, D.,Horvat, M. (2017). Prenatal exposure to low-level methylmercury alters the child’s fine motor skills at the age of 18 months Environ Res, 152(#issue#), 369-374 | Intervention/exposure vs comparator
446 | Pruszkowska-Przybylska, P.,Sitek, A.,Rosset, I.,Sobalska-Kwapis, M.,Słomka, M.,Strapagiel, D.,Ż (2018). Association of the 2D:4D digit ratio with body composition among the Polish children aged 6–13years Early Human Development, 124(#issue#), 26-32 | Study design, Intervention/exposure vs comparator
447 | Puccio, G.,Alliet, P.,Cajozzo, C.,Janssens, E.,Corsello, G.,Sprenger, N.,Wernimont, S.,Egli, D.,Gosoniu, L.,Steenhout, P. (2017). Effects of Infant Formula With Human Milk Oligosaccharides on Growth and Morbidity: A Randomized Multicenter Trial J Pediatr Gastroenterol Nutr, 64(4), 624-631 | Intervention/exposure vs comparator
448 | Putet, G.,Labaune, J. M.,Mace, K.,Steenhout, P.,Grathwohl, D.,Raverot, V.,Morel, Y.,Picaud, J. C. (2016). Effect of dietary protein on plasma insulin-like growth factor-1, growth, and body composition in healthy term infants: a randomised, double-blind, controlled trial (Early Protein and Obesity in Childhood (EPOCH) study) Br J Nutr, 115(2), 271-84 | Already included in P/B24 search
449 | Radke, M.,Picaud, J. C.,Loui, A.,Cambonie, G.,Faas, D.,Lafeber, H. N.,de Groot, N.,Pecquet, S. S.,Steenhout, P. G.,Hascoet, J. M. (2017). Starter formula enriched in prebiotics and probiotics ensures normal growth of infants and promotes gut health: a randomized clinical trial Pediatr Res, 81(4), 622-631 | Outcome
450 | Radke, Michael,Picaud, Jean-Charles,Loui, Andrea,Cambonie, Gilles,Faas, Dirk,Lafeber, Harry N.,de Groot, Nanda,Pecquet, Sophie S.,Steenhout, Philippe G.,Hascoet, Jean-Michel (2016). Starter formula enriched in prebiotics and probiotics ensures normal growth of infants and promotes gut health: a randomized clinical trial Pediatric Research, #volume#(#issue#), N.PAG-N.PAG | Duplicate
451 | Ramos, Jose Geraldo,Strapasson, Márcia Rejane,Ferreira, Charles Francisco (2018). 26. Breastfeeding practices in the first 6 months after delivery: Effects of arterial hypertension Pregnancy Hypertension, 13(#issue#), S57-S57 | Publication status
452 | Ranucci, G.,Buccigrossi, V.,Borgia, E.,Piacentini, D.,Visentin, F.,Cantarutti, L.,Baiardi, P.,Felisi, M. G.,Spagnuolo, M. I.,Zanconato, S.,et al, (2018). Association between environmental determinants and intestinal microbiota structure in the development of atopic dermatitis in infants at high risk of atopy Journal of pediatric gastroenterology and nutrition, 66(#issue#), 1162- | Publication status
453 | Ranucci, G.,Buccigrossi, V.,Borgia, E.,Piacentini, D.,Visentin, F.,Cantarutti, L.,Baiardi, P.,Felisi, M.,Spagnuolo, M. I.,Zanconato, S.,Baraldi, E.,Giaquinto, C.,Guarino, A. (2018). Galacto-Oligosaccharide/Polidextrose Enriched Formula Protects against Respiratory Infections in Infants at High Risk of Atopy: A Randomized Clinical Trial Nutrients, 10(3), #Pages# | Outcome
454 | Rao, D. P.,Kropac, E.,Do, M. T.,Roberts, K. C.,Jayaraman, G. C. (2017). Status report -- Childhood overweight and obesity in Canada: an integrative assessment Health Promot Chronic Dis Prev Can, 37(3), 87-93 | Study design
455 | Rauschert, S.,Mori, T. A.,Beilin, L. J.,Jacoby, P.,Uhl, O.,Koletzko, B.,Oddy, W. H.,Hellmuth, C. (2017). Early Life Factors, Obesity Risk, and the Metabolome of Young Adults Obesity (Silver Spring), 25(9), 1549-1555 | Outcome
456 | Rautava, S. (2018). Probiotic Intervention Through the Pregnant and Breastfeeding Mother to Reduce Disease Risk in the Child Breastfeed Med, 13(S1), S14-s15 | Study design
457 | Ray, S.,Seth, A.,Baijal, N.,Singh, S.,Sharma, G.,Kumar, P.,Chandra, J. (2019). Comparison of Feeding Options for HIV-Exposed Infants: A Retrospective Cohort Study Indian Pediatr, 56(6), 476-480 | Country
458 | Reifsnider, E.,McCormick, D. P.,Cullen, K. W.,Todd, M.,Moramarco, M. W.,Gallagher, M. R.,Reyna, L. (2018). Randomized Controlled Trial to Prevent Infant Overweight in a High-Risk Population Acad Pediatr, 18(3), 324-333 | Intervention/exposure vs comparator
459 | Reis-Santos, B.,Barros, F. C.,Horta, B. L. (2018). Is there a causal effect of parity on body composition: a birth cohort study BMC Public Health, 18(1), 215 | Intervention/exposure vs comparator
460 | Rejali, M.,Pahlavni, S.,Hassanzadeh, A. (2017). Evaluation of 1-year-old children development in Isfahan City and its effective factors using ages and stages questionnaire, in 2014 J Educ Health Promot, 6(#issue#), 57 | ConfoundersStudy design
461 | Rendina, D. N.,Blohowiak, S. E.,Coe, C. L.,Kling, P. J. (2018). Maternal Perceived Stress during Pregnancy Increases Risk for Low Neonatal Iron at Delivery and Depletion of Storage Iron at One Year J Pediatr, 200(#issue#), 166-173.e2 | Study design, Intervention/exposure vs comparator
462 | Riano-Galan, I.,Fernandez-Somoano, A.,Rodriguez-Dehli, C.,Valvi, D.,Vrijheid, M.,Tardon, A. (2017). Proatherogenic Lipid Profile in Early Childhood: Association with Weight Status at 4 Years and Parental Obesity J Pediatr, 187(#issue#), 153-157.e2 | Intervention/exposure vs comparator
463 | Robbins, K. A.,Uygungil, B. (2017). Nutritional Deficiencies and Food Allergy J Allergy Clin Immunol Pract, 5(2), 528-529 | Study design
464 | Rodriguez-Cano, A. M.,Mier-Cabrera, J.,Allegre-Davalos, A. L.,Munoz-Manrique, C.,Perichart-Perera, O. (2019). Higher fat mass and fat mass accretion during the first six months of life in exclusively breastfed infants Pediatr Res, #volume#(#issue#), #Pages# | Confounders
465 | Rodriguez-Cano, A. M.,Mier-Cabrera, J.,Munoz-Manrique, C.,Cardona-Perez, A.,Villalobos-Alcazar, G.,Perichart-Perera, O. (2019). Anthropometric and clinical correlates of fat mass in healthy term infants at 6 months of age BMC Pediatr, 19(1), 60 | Study design
466 | Rodríguez-Cano, Ameyalli M.,Mier-Cabrera, Jennifer,Muñoz-Manrique, Cinthya,Cardona-Pérez, Arturo,Villalobos-Alcázar, Gicela,Perichart-Perera, Otilia (2019). Anthropometric and clinical correlates of fat mass in healthy term infants at 6 months of age BMC Pediatrics, 19(1), N.PAG-N.PAG
467 | Rodriguez-Herrera, A.,Abrahamse-Berkeveld, M.,Alles, M.,Bouritius, H.,Rubio, R. P.,Munoz, A.,Agosti, M.,Lista, G.,Corvaglia, L. T.,Navero, J. L. P. (2016). A partly fermented infant formula containing scGOS/lcFOS supports adequate growth in healthy, term infants: the life study Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 658-659 | Publication status
468 | Rodriguez-Herrera, A.,Mulder, K.,Bouritius, H.,Rubio, R.,Muñoz, A.,Agosti, M.,Lista, G.,Corvaglia, L.,Ludwig, T.,Abrahamse-Berkeveld, M.,Perez-Navero, J. L. (2019). Gastrointestinal tolerance, growth and safety of a partly fermented formula with specific prebiotics in healthy infants: A double-blind, randomized, controlled trial Nutrients, 11(7), #Pages# | Intervention/exposure vs comparator
469 | Rodriguez-Lopez, M.,Osorio, L.,Acosta-Rojas, R.,Figueras, J.,Cruz-Lemini, M.,Figueras, F.,Bijnens, B.,Gratacos, E.,Crispi, F. (2016). Influence of breastfeeding and postnatal nutrition on cardiovascular remodeling induced by fetal growth restriction Pediatr Res, 79(1-1), 100-6 | Already excluded from P/B24 search
470 | Rogers, S. L.,Blissett, J. (2017). Breastfeeding duration and its relation to weight gain, eating behaviours and positive maternal feeding practices in infancy Appetite, 108(#issue#), 399-406 | Study design, Outcome
471 | Rohan, Annie J. (2017). Breastfeeding, Cognitive and Non-Cognitive Development in Early Childhood: A Population Study MCN: The American Journal of Maternal Child Nursing, 42(5), 302-302 | Publication status
472 | Rose, C. M.,Savage, J. S.,Birch, L. L. (2016). Patterns of early dietary exposures have implications for maternal and child weight outcomes Obesity (Silver Spring), 24(2), 430-8 | Intervention/exposure vs comparator
473 | Ruiz, A. N.,Herrmann, F.,Valbuena, N. S.,Miranda, M. T.,Morera, M.,Folgoso, C. C. (2017). Association of linear growth velocity and behavior at 18 months of life in healthy children Journal of pediatric gastroenterology and nutrition, 64(#issue#), 923- | Publication status
474 | Rzehak, P.,Oddy, W. H.,Mearin, M. L.,Grote, V.,Mori, T. A.,Szajewska, H.,Shamir, R.,Koletzko, S.,Weber, M.,Beilin, L. J.,Huang, R. C.,Koletzko, B. (2017). Infant feeding and growth trajectory patterns in childhood and body composition in young adulthood Am J Clin Nutr, 106(2), 568-580 | Outcome
475 | Sakihara, T.,Sugiura, S.,Ito, K. (2016). The ingestion of cow’s milk formula in the first 3 months of life prevents the development of cow’s milk allergy Asia Pac Allergy, 6(4), 207-212 | Outcome
476 | Salahuddin, M.,Perez, A.,Ranjit, N.,Hoelscher, D. M.,Kelder, S. H. (2017). The associations of large-for-gestational-age and infant feeding practices with children’s body mass index z-score trajectories: the Early Childhood Longitudinal Study, Birth Cohort Clin Obes, 7(5), 307-315 | Intervention/exposure vs comparator
477 | Salameh, K.,Dawodu, A. H. (2018). Randomized controlled study of effectiveness and safety of high dose vitamine D supplementation on breast milk v D limited sun Journal of pediatric gastroenterology and nutrition, 66(#issue#), 1097- | Publication status
478 | Salas Lorenzo, I.,Chisaguano Tonato, A. M.,de la Garza Puentes, A.,Nieto, A.,Herrmann, F.,Dieguez, E.,Castellote, A. I.,Lopez-Sabater, M. C.,Rodriguez-Palmero, M.,Campoy, C. (2019). The Effect of an Infant Formula Supplemented with AA and DHA on Fatty Acid Levels of Infants with Different FADS Genotypes: The COGNIS Study Nutrients, 11(3), #Pages# | Intervention/exposure vs comparator
479 | Salimar,,Irawati, A.,Besral, (2019). Maternal height as an determinant factors of children not to be stunting until age 59 months Indian Journal of Public Health Research and Development, 10(3), 765-771 | Country
480 | Salo, H. M.,Koponen, J.,Kiviranta, H.,Rantakokko, P.,Honkanen, J.,Härkönen, T.,Ilonen, J.,Virtanen, S. M.,Tillmann, V.,Knip, M.,Vaarala, O. (2019). No evidence of the role of early chemical exposure in the development of β-cell autoimmunity Environmental science and pollution research international, 26(2), 1370-1378 | Outcome
481 | Sanchez-Valverde, F.,Etayo, V.,Gil, F.,Aznal, E.,Martinez, D.,Amezqueta, A.,Mendizabal, M.,Galbete, A.,Pastor, N.,Vanderhoof, J. (2019). Factors Associated with the Development of Immune Tolerance in Children with Cow’s Milk Allergy Int Arch Allergy Immunol, 179(4), 290-296 | Intervention/exposure vs comparator, Participant health
482 | Santos, I. S.,Barros, F. C.,Munhoz, T.,Matijasevich, A. (2017). Gestational age at birth and behavioral problems from four to 11 years of age: birth cohort study BMC Pediatr, 17(1), 184 | Intervention/exposure vs comparator
483 | Santos, L. P.,Assuncao, M. C. F.,Matijasevich, A.,Santos, I. S.,Barros, A. J. D. (2016). Dietary intake patterns of children aged 6 years and their association with socioeconomic and demographic characteristics, early feeding practices and body mass index BMC Public Health, 16(1), 1055 | Outcome
484 | Santos, L. P.,Ong, K. K.,Santos, I. S.,Matijasevich, A.,Barros, A. J. D. (2019). Effects of dietary intake patterns from 1 to 4 years on BMI z-score and body shape at age of 6 years: a prospective birth cohort study from Brazil Eur J Nutr, 58(4), 1723-1734 | Intervention/exposure vs comparator
485 | Sardecka, I.,Los-Rycharska, E.,Ludwig, H.,Gawryjolek, J.,Krogulska, A. (2018). Early risk factors for cow’s milk allergy in children in the first year of life Allergy Asthma Proc, 39(6), e44-e54 | Study design
486 | Sauder, K. A.,Bekelman, T. A.,Harrall, K. K.,Glueck, D. H.,Dabelea, D. (2019). Gestational diabetes exposure and adiposity outcomes in childhood and adolescence: An analysis of effect modification by breastfeeding, diet quality, and physical activity in the EPOCH study Pediatr Obes, #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
487 | Sauder, K. A.,Kaar, J. L.,Starling, A. P.,Ringham, B. M.,Glueck, D. H.,Dabelea, D. (2017). Predictors of Infant Body Composition at 5 Months of Age: The Healthy Start Study J Pediatr, 183(#issue#), 94-99.e1 | Outcome
488 | Sauder, K. A.,Starling, A. P.,Shapiro, A. L.,Kaar, J. L.,Ringham, B. M.,Glueck, D. H.,Dabelea, D. (2016). Exploring the association between maternal prenatal multivitamin use and early infant growth: The Healthy Start Study Pediatr Obes, 11(5), 434-41 | Intervention/exposure vs comparator
489 | Savage, J. S.,Birch, L. L.,Marini, M.,Anzman-Frasca, S.,Paul, I. M. (2016). Effect of the INSIGHT Responsive Parenting Intervention on Rapid Infant Weight Gain and Overweight Status at Age 1 Year: A Randomized Clinical Trial JAMA Pediatr, 170(8), 742-9 | Outcome
490 | Sbihi, H.,Koehoorn, M.,Tamburic, L.,Brauer, M. (2017). Asthma Trajectories in a Population-based Birth Cohort. Impacts of Air Pollution and Greenness Am J Respir Crit Care Med, 195(5), 607-613 | Outcome
491 | Scalabrin, D.,Harris, C.,Johnston, W. H.,Berseth, C. L. (2017). Long-term safety assessment in children who received hydrolyzed protein formulas with Lactobacillus rhamnosus GG: a 5-year follow-up Eur J Pediatr, 176(2), 217-224 | Intervention/exposure vs comparator
492 | Schwenke, E.,Fasching, P. A.,Faschingbauer, F.,Pretscher, J.,Kehl, S.,Peretz, R.,Keller, A.,Haberle, L.,Eichler, A.,Irlbauer-Muller, V.,Dammer, U.,Beckmann, M. W.,Schneider, M. (2018). Predicting attention deficit hyperactivity disorder using pregnancy and birth characteristics Arch Gynecol Obstet, 298(5), 889-895 | Outcome
493 | Scott-Jupp, R. (2017). Breastfeeding and obesity Arch Dis Child, 102(7), 616 | Outcome
494 | Sekhobo, J. P. (2017). Estimation of WIC effects in multilevel, cross-sector obesity prevention interventions Obesity, 25(7), 1157-1158 | Publication status
495 | Selby, A.,Munro, A.,Grimshaw, K. E.,Cornelius, V.,Keil, T.,Grabenhenrich, L.,Clausen, M.,Dubakiene, R.,Fiocchi, A.,Kowalski, M. L.,Papadopoulos, N. G.,Reche, M.,Sigurdardottir, S. T.,Sprikkelman, A. B.,Xepapadaki, P.,Mills, E. N. C.,Beyer, K.,Roberts, G. (2018). Prevalence estimates and risk factors for early childhood wheeze across Europe: the EuroPrevall birth cohort Thorax, 73(11), 1049-1061 | Outcome
496 | Sen, S.,Penfield-Cyr, A.,Hollis, B. W.,Wagner, C. L. (2017). Maternal Obesity, 25-Hydroxy Vitamin D Concentration, and Bone Density in Breastfeeding Dyads J Pediatr, 187(#issue#), 147-152.e1 | Intervention/exposure vs comparator
497 | Seo, S.,Yoon, W. S.,Cho, Y.,Park, S. H.,Choung, J. T.,Yoo, Y. (2016). Leptin and Atopic Dermatitis in Korean Elementary School Children Iran J Allergy Asthma Immunol, 15(2), 138-44 | Outcome
498 | Seppo, A. E.,Autran, C. A.,Bode, L.,Järvinen, K. M. (2017). Human milk oligosaccharides and development of cow’s milk allergy in infants Journal of Allergy and Clinical Immunology, 139(2), 708-711.e5 | Publication status
499 | Shahramian, I.,Kalvandi, G.,Javaherizadeh, H.,Khalili, M.,Noori, N. M.,Delaramnasab, M.,Bazi, A. (2018). The effects of prebiotic supplementation on weight gain, diarrhoea, constipation, fever and respiratory tract infections in the first year of life Journal of Paediatrics and Child Health, 54(8), 875-880 | Intervention/exposure vs comparator
500 | Shalitin, Shlomit,Battelino, Tadej,Moreno, Luis A. (2017). Obesity, Metabolic Syndrome, and Nutrition World Review of Nutrition & Dietetics, 116(#issue#), 16-51 | Publication status, Study design
501 | Sharma, A. K.,Gallo, S.,Vanstone, C. A.,Agellon, S.,L’Abbe, M.,Khamessan, A.,Comeau, K.,Weiler, H. A.,Rodd, C. (2016). Parathyroid hormone-ionized calcium dynamics over the first year of life J Pediatr Endocrinol Metab, 29(6), 709-14 | Intervention/exposure vs comparator
502 | Shashaj, B.,Graziani, M. P.,Contoli, B.,Ciuffo, C.,Cives, C.,Facciolini, S.,Rigoni, M. L.,Spaterna, S.,Taucci, M.,Raponi, M.,Manco, M. (2016). Energy Balance–Related Behaviors, Perinatal, Sociodemographic, and Parental Risk Factors Associated with Obesity in Italian Preschoolers Journal of the American College of Nutrition, 35(4), 362-371 | Study design
503 | Sherwood, W. B.,Bion, V.,Lockett, G. A.,Ziyab, A. H.,Soto-Ramirez, N.,Mukherjee, N.,Kurukulaaratchy, R. J.,Ewart, S.,Zhang, H.,Arshad, S. H.,Karmaus, W.,Holloway, J. W.,Rezwan, F. I. (2019). Duration of breastfeeding is associated with leptin (LEP) DNA methylation profiles and BMI in 10-year-old children Clin Epigenetics, 11(1), 128 | Confounders
504 | Shi, J.,Tan, D.,Xie, H.,Yang, B.,Liu, R.,Yu, D.,Lu, Y.,Mei, B.,Wang, Z. (2017). Unequal Distribution of Overweight Adolescents in Immigrant-Rich Areas: Analysis of Disparities among Public and Private School Students in Shanghai, China Int J Environ Res Public Health, 14(3), #Pages# | Study design
505 | Shinn, L. M.,Tangney, C. C.,Busche, C.,Sharp, C. M.,Mullen, M. C. (2018). Demographic Correlates of Infant Feeding Practices and Growth Performance in the First Year of Life Int J Pediatr, 2018(#issue#), 6569204 | Intervention/exposure vs comparator
506 | Shoaibi, A.,Neelon, B.,Ostbye, T.,Benjamin-Neelon, S. E. (2019). Longitudinal associations of gross motor development, motor milestone achievement and weight-for-length z score in a racially diverse cohort of US infants BMJ Open, 9(1), e024440 | Intervention/exposure vs comparator
507 | Sicherer, S. H.,Wood, R. A.,Perry, T. T.,Jones, S. M.,Leung, D. Y. M.,Henning, A. K.,Dawson, P.,Burks, A. W.,Lindblad, R.,Sampson, H. A. (2019). Clinical factors associated with peanut allergy in a high-risk infant cohort Allergy, #volume#(#issue#), #Pages# | Outcome
508 | Singhal, A. (2019). The Impact of Human Milk Feeding on Long-Term Risk of Obesity and Cardiovascular Disease Breastfeed Med, 14(S1), S9-s10 | Study design
509 | Sinno, D.,Tamim, H.,Faytrouni, F.,Mikati, M. A.,Charafeddine, L. (2018). Factors affecting child development assessed by the Ages and Stages Questionnaire (ASQ) in an Arabic speaking population Early Hum Dev, 120(#issue#), 61-66 | Study design, Intervention/exposure vs comparator
510 | Sirkka, O.,Vrijkotte, T.,Halberstadt, J.,Abrahamse-Berkeveld, M.,Hoekstra, T.,Seidell, J.,Olthof, M. (2018). Prospective associations of age at complementary feeding and exclusive breastfeeding duration with body mass index at 5-6 years within different risk groups Pediatr Obes, 13(8), 522-529 | Intervention/exposure vs comparator
511 | Sitarik, A. R.,Kasmikha, N. S.,Kim, H.,Wegienka, G.,Havstad, S.,Ownby, D.,Zoratti, E.,Johnson, C. C. (2018). Breast-feeding and delivery mode modify the association between maternal atopy and childhood allergic outcomes Journal of Allergy and Clinical Immunology, 142(6), 2002-2004.e2 | Publication status
512 | Slomski, A. (2018). Neurocognitive Benefits from Breastfeeding May Not Endure Jama, 319(24), 2470 | Publication status
513 | Slupsky, C. M.,He, X.,Hernell, O.,Andersson, Y.,Rudolph, C.,Lonnerdal, B.,West, C. E. (2017). Postprandial metabolic response of breast-fed infants and infants fed lactose-free vs regular infant formula: A randomized controlled trial Sci Rep, 7(1), 3640 | Intervention/exposure vs comparator, Size of study groups
514 | Soto-Ramirez, N.,Kar, S.,Zhang, H.,Karmaus, W. (2017). Infant feeding patterns and eczema in children in the first 6 years of life Clin Exp Allergy, 47(10), 1285-1298 | Outcome
515 | Sotunde, O. F.,Gallo, S.,Vanstone, C. A.,Weiler, H. A. (2018). Normative Data for Lean Mass and Fat Mass in Healthy Predominantly Breast-Fed Term Infants From 1 Month to 1 Year of Age J Clin Densitom, #volume#(#issue#), #Pages# | Intervention/exposure vs comparator
516 | Souza, C. O.,Leite, M. E. Q.,Lasekan, J.,Baggs, G.,Pinho, L. S.,Druzian, J. I.,Ribeiro, T. C. M.,Mattos, A. P.,Menezes-Filho, J. A.,Costa-Ribeiro, H. (2017). Milk protein-based formulas containing different oils affect fatty acids balance in term infants: A randomized blinded crossover clinical trial Lipids Health Dis, 16(1), 78 | Intervention/exposure vs comparator
517 | Spalinger, J.,Nydegger, A.,Belli, D.,Furlano, R. I.,Yan, J.,Tanguy, J.,Pecquet, S.,Destaillats, F.,Egli, D.,Steenhout, P. (2017). Growth of infants fed formula with evolving nutrition composition: A single-arm non-inferiority study Nutrients, 9(3), #Pages# | Intervention/exposure vs comparator
518 | St John, A. M.,Kao, K.,Liederman, J.,Grieve, P. G.,Tarullo, A. R. (2017). Maternal cortisol slope at 6 months predicts infant cortisol slope and EEG power at 12 months Developmental psychobiology, 59(6), 787-801 | Intervention/exposure vs comparator
519 | Standl, M.,Schulte-Korne, G.,Heinrich, J. (2016). Breastfeeding and symptoms of dyslexia in children and adolescents European journal of epidemiology, Conference: Health - Exploring Complexity: An Interdisciplinary Systems Approach, HEC 2016. Germany. Conference Start: 20160828. Conference End: 20160902. 31(#issue#), S193-S194 | Publication status
520 | Stanford, F. C. (2016). Obesity and Breastfeeding: Exploring the Relationship Breastfeed Med, 11(#issue#), 411-2 | Study design
521 | Stelmach, I.,Kwarta, P.,Jerzynska, J.,Stelmach, W.,Krakowiak, J.,Karbownik, M.,Podlecka, D.,Hanke, W.,Polanska, K. (2019). Duration of breastfeeding and psychomotor development in 1-year-old children - Polish Mother and Child Cohort Study Int J Occup Med Environ Health, 32(2), 175-184 | Study design
522 | Stemeseder, T.,Klinglmayr, E.,Moser, S.,Lang, R.,Himly, M.,Oostingh, G. J.,Zumbach, J.,Bathke, A. C.,Hawranek, T.,Gadermaier, G. (2017). Influence of Intrinsic and Lifestyle Factors on the Development of IgE Sensitization Int Arch Allergy Immunol, 173(2), 99-104 | Outcome
523 | Stergiakouli, E.,Martin, J.,Hamshere, M.,St Pourcain, B.,Timpson, N.,Thapar, A.,Smith, G. D. (2017). Shared genetic effects between clinical ADHD and smoking, alcohol and breastfeeding in mothers from the general population European neuropsychopharmacology, 27(#issue#), S141- | Publication status
524 | Stranak, Z.,Feyereislova, S.,Cerna, M.,Kollarova, J.,Feyereisl, J. (2016). Limited Amount of Formula May Facilitate Breastfeeding: Randomized, Controlled Trial to Compare Standard Clinical Practice versus Limited Supplemental Feeding PLoS One, 11(2), e0150053 | OutcomeOutcome
525 | Straub, N.,Grunert, P.,Northstone, K.,Emmett, P. (2016). Economic impact of breast-feeding-associated improvements of childhood cognitive development, based on data from the ALSPAC Br J Nutr, #volume#(#issue#), 1-6 | Outcome
526 | Strom, M.,Mortensen, E. L.,Kesmodel, U. S.,Halldorsson, T.,Olsen, J.,Olsen, S. F. (2019). Is breast feeding associated with offspring IQ at age 5? Findings from prospective cohort: Lifestyle During Pregnancy Study BMJ Open, 9(5), e023134 | Outcome
527 | Stromberg Celind, F.,Wennergren, G.,Vasileiadou, S.,Alm, B.,Goksor, E. (2018). Antibiotics in the first week of life were associated with atopic asthma at 12 years of age Acta Paediatr, 107(10), 1798-1804 | Intervention/exposure vs comparator
528 | Stuart, B.,Panico, L. (2016). Early-childhood BMI trajectories: evidence from a prospective, nationally representative British cohort study Nutr Diabetes, 6(#issue#), e198 | Outcome
529 | Subhan, F. B.,Colman, I.,McCargar, L.,Bell, R. C. (2017). Higher Pre-pregnancy BMI and Excessive Gestational Weight Gain are Risk Factors for Rapid Weight Gain in Infants Matern Child Health J, 21(6), 1396-1407 | Confounders, Intervention/exposure vs comparator
530 | Sukumar, N.,Saravanan, P. (2019). Investigating vitamin B12 deficiency BMJ (Online), 365(#issue#), #Pages# | Study design
531 | Sutin, A. R.,Stephan, Y.,Terracciano, A. (2016). Breastfeeding and Adult Personality Eur J Pers, 30(5), 484-491 | Outcome
532 | Szabelska-Zakrzewska, K.,Durko, A.,Socha-Banasiak, A.,Majewska, M.,Kolejwa, M.,Kazanek-Zasada, J.,Czkwianianc, E. (2018). Metabolic syndrome in overweight or obese children and adolescents based on own material Abstract Key words Dev Period Med, 22(4), 351-357 | Study design, Outcome
533 | Szajewska, H.,Ruszczynski, M.,Szymanski, H.,Sadowska-Krawczenko, I.,Piwowarczyk, A.,Rasmussen, P. B.,Kristensen, M. B.,West, C. E.,Hernell, O. (2017). Effects of infant formula supplemented with prebiotics compared with synbiotics on growth up to the age of 12 mo: a randomized controlled trial Pediatr Res, 81(5), 752-758 | Outcome
534 | Szymlek-Gay, E. A.,Domellof, M.,Hernell, O.,Hurrell, R. F.,Lind, T.,Lonnerdal, B.,Zeder, C.,Egli, I. M. (2016). Mode of oral iron administration and the amount of iron habitually consumed do not affect iron absorption, systemic iron utilisation or zinc absorption in iron-sufficient infants: a randomised trial Br J Nutr, 116(6), 1046-60 | Intervention/exposure vs comparator
535 | Tambalis, K. D.,Mourtakos, S.,Panagiotakos, D. B.,Sidossis, L. S. (2018). Association of Exclusive Breastfeeding with Risk of Obesity in Childhood and Early Adulthood Breastfeed Med, #volume#(#issue#), #Pages# | Study design
536 | Tanaka, K.,Miyake, Y.,Furukawa, S.,Arakawa, M. (2016). Perinatal smoking exposure and behavioral problems in Japanese children aged 5 years: The Kyushu Okinawa Maternal and Child Health Study Environmental Research, 151(#issue#), 383-388 | Intervention/exposure vs comparator
537 | Tang, M.,Griese, K. E.,Krebs, N. F. (2016). Dietary intakes of formula-fed infants consuming a meat-or dairy-based complementary diet: a semi-controlled feeding trial FASEB journal. Conference: experimental biology 2016, EB. San diego, CA united states. Conference start: 20160402. Conference end: 20160406. Conference publication: (var.pagings), 30(no pagination), #Pages# | Publication status
538 | Tang, M.,Rijnierse, A.,Nauta, A.,Boyle, R.,Hourihane, J.,Chiang, W.,Chua, M.,Smith, P.,Gold, M.,Ziegler, J.,et al, (2017). Influence of early feeding patterns on eczema development in high-risk infants Allergy, 72(#issue#), 15- | Publication status
539 | Taylor, B.,Taylor, R.,Gray, A.,Galland, B.,Heath, A.,Lawrence, J.,Hanna, M.,Hatch, B. (2017). The prevention of obesity in infancy by targeting sleep or food and activity: RCT outcomes at 5 years Obesity facts, 10(#issue#), 23- | Publication status
540 | Taylor-Robinson, D. C.,Williams, H.,Pearce, A.,Law, C.,Hope, S. (2016). Do early-life exposures explain why more advantaged children get eczema? Findings from the U.K. Millennium Cohort Study Br J Dermatol, 174(3), 569-78 | Outcome
541 | Terashita, S.,Nakamura, T.,Igarashi, N. (2017). Longitudinal study on the effectiveness of vitamin D supplements in exclusively breast-fed infants Clin Pediatr Endocrinol, 26(4), 215-222 | Intervention/exposure vs comparator
542 | Tham, E. H.,Lee, B. W.,Chan, Y. H.,Loo, E. X. L.,Toh, J. Y.,Goh, A.,Teoh, O. H.,Yap, F.,Tan, K. H.,Godfrey, K. M.,Chong, M. F. F.,Van Bever, H. P. S.,Chong, Y. S.,Shek, L. P. (2018). Low Food Allergy Prevalence Despite Delayed Introduction of Allergenic Foods-Data from the GUSTO Cohort J Allergy Clin Immunol Pract, 6(2), 466-475.e1 | Outcome
543 | Thorisdottir, B.,Gunnarsdottir, I.,Steingrimsdottir, L.,Palsson, G. I.,Birgisdottir, B. E.,Thorsdottir, I. (2016). Vitamin D Intake and Status in 6-Year-Old Icelandic Children Followed up from Infancy Nutrients, 8(2), 75 | Outcome
544 | Thorisdottir, B.,Gunnarsdottir, I.,Vidarsdottir, A. G.,Sigurdardottir, S.,Birgisdottir, B. E.,Thorsdottir, I. (2019). Infant Feeding, Vitamin D and IgE Sensitization to Food Allergens at 6 Years in a Longitudinal Icelandic Cohort Nutrients, 11(7), #Pages# | Intervention/exposure vs comparator
545 | Thorland, W.,Currie, D.,Colangelo, C. (2017). Status of High Body Weight Among Nurse-Family Partnership Children MCN Am J Matern Child Nurs, 42(6), 352-357 | Outcome
546 | Tobolic, T. J. (2019). Primum Non Nocere Breastfeeding Breastfeed Med, 14(1), 77-78 | Study design
547 | Totzauer, M.,Luque, V.,Escribano, J.,Closa-Monasterolo, R.,Verduci, E.,ReDionigi, A.,Hoyos, J.,Langhendries, J. P.,Gruszfeld, D.,Socha, P.,Koletzko, B.,Grote, V. (2018). Effect of Lower Versus Higher Protein Content in Infant Formula Through the First Year on Body Composition from 1 to 6 Years: Follow-Up of a Randomized Clinical Trial Obesity (Silver Spring), 26(7), 1203-1210 | Intervention/exposure vs comparator
548 | Troesch, B.,Demmelmair, J.,Gimpfl, M.,Hecht, C.,Lakovic, G.,Roehle, R.,Sipka, L.,Trisic, B.,Vusurovic, M.,Schoop, R.,Zdjelar, S.,Koletzko, B. (2019). Suitability and safety of L-5-methyltetrahydrofolate as a folate source in infant formula: A randomized-controlled trial PLoS One, 14(8), e0216790 | Intervention/exposure vs comparator
549 | Tse, S. M.,Rifas-Shiman, S. L.,Coull, B. A.,Litonjua, A. A.,Oken, E.,Gold, D. R. (2016). Sex-specific risk factors for childhood wheeze and longitudinal phenotypes of wheeze J Allergy Clin Immunol, 138(6), 1561-1568.e6 | Outcome
550 | Tsoucalas, G.,Sgantzos, M. (2017). Oribasius-Pediatric Skin Eruptions and the Origins of the Allergic Reaction to Breast Milk JAMA Dermatol, 153(4), 303 | Outcome
551 | Uğraş Dikmen, A.,Konşuk Ünlü, H.,Özcebe, L. H. (2019). Evaluation of being overweight/obese and related sociodemographic factors in 0-5 year age group in Turkey: Turkey demographic health survey 2013 advanced analysis Turkish Journal of Medical Sciences, 49(3), 879-887 | Study design
552 | Uhl, O.,Fleddermann, M.,Hellmuth, C.,Demmelmair, H.,Koletzko, B. (2016). Phospholipid Species in Newborn and 4 Month Old Infants after Consumption of Different Formulas or Breast Milk PLoS One, 11(8), e0162040 | Intervention/exposure vs comparator
553 | Umer, A.,Hamilton, C.,Edwards, R. A.,Cottrell, L.,Giacobbi, P., Jr.,Innes, K.,John, C.,Kelley, G. A.,Neal, W.,Lilly, C. (2019). Association Between Breastfeeding and Childhood Cardiovascular Disease Risk Factors Matern Child Health J, 23(2), 228-239 | Study design
554 | Uusitalo, U.,Lee, H. S.,Andren Aronsson, C.,Vehik, K.,Yang, J.,Hummel, S.,Silvis, K.,Lernmark, A.,Rewers, M.,Hagopian, W.,She, J. X.,Simell, O.,Toppari, J.,Ziegler, A. G.,Akolkar, B.,Krischer, J.,Virtanen, S. M.,Norris, J. M. (2018). Early Infant Diet and Islet Autoimmunity in the TEDDY Study Diabetes Care, 41(3), 522-530 | Outcome
555 | van der Willik, Esmee,Vrijkotte, Tanja G. M.,Altenburg, Teatske M.,Gademan, Maaike G. J.,Kist-van Holthe, Joana (2016). Exclusively breastfed overweight infants are at the same risk of childhood overweight as formula fed overweight infants MIDIRS Midwifery Digest, 26(1), 101-102 | Publication status Intervention/exposure vs comparator
556 | van der Wurff, I. S.,Bakker, E. C.,Hornstra, G.,Kirschner, P. A.,Gielen, M.,Godschalk, R. W.,Kremers, S.,Zeegers, M. P.,de Groot, R. H. (2016). Association between prenatal and current exposure to selected LCPUFAs and school performance at age 7 Prostaglandins Leukot Essent Fatty Acids, 108(#issue#), 22-9 | Study design, Intervention/exposure vs comparator
557 | van Ginkel, C. D.,van der Meulen, G. N.,Bak, E.,Flokstra-de Blok, B. M. J.,Kollen, B. J.,Koppelman, G. H.,Dubois, A. E. J. (2018). Retrospective observational cohort study regarding the effect of breastfeeding on challenge-proven food allergy Eur J Clin Nutr, 72(4), 557-563 | Outcome
558 | van Meel, E. R.,de Jong, M.,Elbert, N. J.,den Dekker, H. T.,Reiss, I. K.,de Jongste, J. C.,Jaddoe, V. W. V.,Duijts, L. (2017). Duration and exclusiveness of breastfeeding and school-age lung function and asthma Ann Allergy Asthma Immunol, 119(1), 21-26.e2 | Outcome
559 | van Rossem, L.,Smit, H. A.,Lentjes, Egwm,Maitimu-Smeele, I.,Brunekreef, B.,Koppelman, G. H.,Wijga, A. H. (2019). Does breast milk adiponectin affect BMI and cardio-metabolic markers in childhood? Br J Nutr, 121(8), 905-913 | Intervention/exposure vs comparator
560 | van Steenkiste, K. (2016). [Not Available] Kinderkrankenschwester, 35(7), 248-249 | Publication status
561 | van Wouwe, Jacobus P.,Lanting, Caren I.,Akkermans, Marjolijn D.,Eussen, Simone R. B. M.,van der Horst-Graat, Judith M.,van Elburg, Ruurd M.,van Goudoever, Johannes B.,Brus, Frank (2017). More ways to successfully supplement vitamin D…Akkermans MD, Eussen SRBM, van der Horst-Graat JM, van Elburg RM, van Goudoever JB, Brus F. A micronutrient-fortified young-child formula improves the iron and vitamin D status of healthy young European children: a randomized, double-blind controlled trial. Am J Clin Nutr 2017;105:391–9 #journal#, 105(#issue#), 1564-1566 | Publication status
562 | Vandyousefi, S.,Goran, M. I.,Gunderson, E. P.,Khazaee, E.,Landry, M. J.,Ghaddar, R.,Asigbee, F. M.,Davis, J. N. (2019). Association of breastfeeding and gestational diabetes mellitus with the prevalence of prediabetes and the metabolic syndrome in offspring of Hispanic mothers Pediatr Obes, 14(7), e12515 | Intervention/exposure vs comparator
563 | Varsi, Kristin,Bolann, Bjørn,Torsvik, Ingrid,Rosvold Eik, Tina Constanse,Høl, Paul Johan,Bjørke-Monsen, Anne-Lise (2017). Impact of Maternal Selenium Status on Infant Outcome during the First 6 Months of Life Nutrients, 9(5), 486 | Intervention/exposure vs comparator
564 | Vehapoglu, A.,Goknar, N.,Turel, O.,Torun, E.,Ozgurhan, G. (2017). Risk factors for childhood obesity: Do the birth weight, type of delivery, and mother’s overweight have an implication on current weight status? World J Pediatr, 13(5), 457-464 | Study design, Intervention/exposure vs comparator
565 | Veile, A.,Faria, A. A.,Rivera, S.,Tuller, S. M.,Kramer, K. L. (2019). Birth mode, breastfeeding and childhood infectious morbidity in the Yucatec Maya Am J Hum Biol, #volume#(#issue#), e23218 | Outcome
566 | Venter, C.,Maslin, K.,Dean, T.,Arshad, S. H. (2016). Does concurrent breastfeeding alongside the introduction of solid food prevent the development of food allergy? J Nutr Sci, 5(#issue#), e40 | Outcome
567 | Ventura, A. K. (2017). Developmental Trajectories of Bottle-Feeding During Infancy and Their Association with Weight Gain J Dev Behav Pediatr, 38(2), 109-119 | Outcome
568 | Ventura, A. K.,Thompson, K. (2019). Predictors of Resilience Among Infants at Risk for Rapid Weight Gain Obesity (Silver Spring), 27(1), 130-136 | Intervention/exposure vs comparator
569 | Vergara Perez, Ines,Vila Sexto, Leticia (2018). Suspected severe acute food protein-induced enterocolitis syndrome caused by cow’s milk through breast milk Annals of Allergy, Asthma & Immunology, 121(2), 245-246 | Study design
570 | Vianna, C. A.,Horta, B. L.,Gigante, D. P.,de Barros, F. C. (2016). Pulse Wave Velocity at Early Adulthood: Breastfeeding and Nutrition during Pregnancy and Childhood PLoS One, 11(4), e0152501 | Outcome
571 | Viljoen, K.,Segurado, R.,O’Brien, J.,Murrin, C.,Mehegan, J.,Kelleher, C. C. (2018). Pregnancy diet and offspring asthma risk over a 10-year period: the Lifeways Cross Generation Cohort Study, Ireland BMJ Open, 8(2), e017013 | Outcome
572 | Viner, R. M.,Costa, S.,Johnson, W. (2019). Patterns of BMI development between 10 and 42 years of age and their determinants in the 1970 British Cohort Study J Epidemiol Community Health, 73(1), 79-85 | Intervention/exposure vs comparator
573 | Vogelezang, S.,Santos, S.,van der Beek, E. M.,Abrahamse-Berkeveld, M.,Duijts, L.,van der Lugt, A.,Felix, J. F.,Jaddoe, V. W. V. (2018). Infant breastfeeding and childhood general, visceral, liver, and pericardial fat measures assessed by magnetic resonance imaging Am J Clin Nutr, 108(4), 722-729 | Outcome
574 | von Berg, A.,Filipiak-Pittroff, B.,Kramer, U.,Link, E.,Heinrich, J.,Koletzko, S.,Grubl, A.,Hoffmann, U.,Beckmann, C.,Reinhardt, D.,Bauer, C. P.,Wichmann, E.,Berdel, D. (2017). The German Infant Nutritional Intervention Study (GINI) for the preventive effect of hydrolyzed infant formulas in infants at high risk for allergic diseases. Design and selected results Allergol Select, 1(1), 28-38 | Outcome
575 | von Berg, A.,Filipiak-Pittroff, B.,Schulz, H.,Hoffmann, U.,Link, E.,Sussmann, M.,Schnappinger, M.,Bruske, I.,Standl, M.,Kramer, U.,Hoffmann, B.,Heinrich, J.,Bauer, C. P.,Koletzko, S.,Berdel, D. (2016). Allergic manifestation 15 years after early intervention with hydrolyzed formulas--the GINI Study Allergy, 71(2), 210-9 | Already excluded from P/B24 search
576 | Von Berg, A.,Filipiak-Pittroff, B.,Schulz, H.,Hoffmann, U.,Link, E.,Sußmann, M.,Schnappinger, M.,Brüske, I.,Standl, M.,Krämer, U.,Hoffmann, B.,Heinrich, J.,Bauer, C. P.,Koletzko, S.,Berdel, D. (2016). Allergic manifestation 15 years after early intervention with hydrolyzed formulas - The GINI Study Allergy: European Journal of Allergy and Clinical Immunology, 71(2), 210-219 | Outcome
577 | von Weikersthal, G. F. (2016). New chances in allergy risk: prevention by breastfeeding, HA food and care from the beginning Kinderkrankenschwester : organ der sektion kinderkrankenpflege, 35(5), 165-168 | Outcome
578 | Wagner, C. L.,Eidelman, Arthur I. (2018). The Impact of Vitamin D on the Maternal and Infant Epigenome: The Role of Pregnancy and Breastfeeding Breastfeeding Medicine, 13(5), 305-306 | Study design
579 | Wallby, T.,Lagerberg, D.,Magnusson, M. (2017). Relationship Between Breastfeeding and Early Childhood Obesity: Results of a Prospective Longitudinal Study from Birth to 4 Years Breastfeed Med, 12(#issue#), 48-53 | Outcome
580 | Wang, A. H.,Fitzpatrick, C. (2019). Which Early Childhood Experiences and Skills Predict Kindergarten Working Memory? J Dev Behav Pediatr, 40(1), 40-48 | Study design
581 | Wang, F.,Liu, H.,Wan, Y.,Li, J.,Chen, Y.,Zheng, J.,Huang, T.,Li, D. (2016). Prolonged Exclusive Breastfeeding Duration Is Positively Associated with Risk of Anemia in Infants Aged 12 Months J Nutr, 146(9), 1707-13 | Intervention/exposure vs comparator
582 | Wang, H.,Mueller, N. T.,Li, J.,Sun, N.,Huo, Y.,Ren, F.,Wang, X. (2017). Association of Maternal Plasma Folate and Cardiometabolic Risk Factors in Pregnancy with Elevated Blood Pressure of Offspring in Childhood Am J Hypertens, 30(5), 532-540 | Outcome
583 | Wang, I. J.,Wen, H. J.,Chiang, T. L.,Lin, S. J.,Guo, Y. L. (2016). Maternal psychologic problems increased the risk of childhood atopic dermatitis Pediatr Allergy Immunol, 27(2), 169-76 | Outcome
584 | Wang, J.,Groetch, M. (2017). Preventing food allergies with tweaks to the infant diet: A practical reality? Annals of Allergy, Asthma and Immunology, 118(4), 385-388 | Publication status
585 | Wang, J.,Ramette, A.,Jurca, M.,Goutaki, M.,Beardsmore, C. S.,Kuehni, C. E. (2017). Association between breastfeeding and eczema during childhood and adolescence: A cohort study PLoS One, 12(9), e0185066 | Outcome
586 | Wang, L.,Collins, C.,Ratliff, M.,Xie, B.,Wang, Y. (2017). Breastfeeding Reduces Childhood Obesity Risks Child Obes, 13(3), 197-204 | Outcome
587 | Wang, L.,van Grieken, A.,Yang-Huang, J.,Vlasblom, E.,L’Hoir, M. P.,Boere-Boonekamp, M. M.,Raat, H. (2018). Relationship between socioeconomic status and weight gain during infancy: The BeeBOFT study PLoS One, 13(11), e0205734 | Intervention/exposure vs comparator
588 | Wang, P.,Hao, M.,Han, W.,Yamauchi, T. (2019). Factors associated with nutritional status and motor development among young children Nurs Health Sci, #volume#(#issue#), #Pages# | Study design
589 | Wang, W.,Sun, Y.,Zhang, M.,Zhang, Y.,Chen, W.,Tan, L.,Shen, J.,Zhao, Z.,Lan, S.,Zhang, W. (2018). Breast milk and infant iodine status during the first 12 weeks of lactation in Tianjin City, China Asia Pac J Clin Nutr, 27(2), 393-398 | Study design, Intervention/exposure vs comparator
590 | Wang, X.,Gao, X.,Yang, Q.,Wang, X.,Li, S.,Jiang, F.,Zhang, J.,Ouyang, F. (2017). Sleep disorders and allergic diseases in Chinese toddlers Sleep Med, 37(#issue#), 174-179 | Study design
591 | Warstedt, K.,Furuhjelm, C.,Falth-Magnusson, K.,Fageras, M.,Duchen, K. (2016). High levels of omega-3 fatty acids in milk from omega-3 fatty acid-supplemented mothers are related to less immunoglobulin E-associated disease in infancy Acta Paediatr, 105(11), 1337-1347 | Outcome
592 | Weber, M.,Luque, V.,Escribano, J.,Closa, R.,Verduci, E.,ReDionigi, A.,Hoyos, J.,Langhendries, J. P.,Gruszfeld, D.,Socha, P.,et al, (2016). Effect of early protein supply on body fat deposition during infancy and childhood: a randomized trial Journal of pediatric gastroenterology and nutrition. Conference: 49th annual meeting of the european society for paediatric gastroenterology, hepatology and nutrition, ESPGHAN 2016. Athens greece. Conference start: 20160525. Conference end: 20160528. Conference publication: (var.pagings), 62(#issue#), 668-669 | Publication status
593 | Whaley, S. E.,Koleilat, M.,Leonard, S.,Whaley, M. (2017). Breastfeeding Is Associated With Reduced Obesity in Hispanic 2- to 5-Year-Olds Served by WIC J Nutr Educ Behav, 49(7 Suppl 2), S144-S150.e1 | Outcome
594 | Wheeler, B. J.,Taylor, B. J.,de Lange, M.,Harper, M. J.,Jones, S.,Mekhail, A.,Houghton, L. A. (2018). A Longitudinal Study of 25-Hydroxy Vitamin D and Parathyroid Hormone Status throughout Pregnancy and Exclusive Lactation in New Zealand Mothers and Their Infants at 45 degrees S Nutrients, 10(1), #Pages# | Intervention/exposure vs comparator
595 | Wheeler, B. J.,Taylor, B. J.,Herbison, P.,Haszard, J. J.,Mikhail, A.,Jones, S.,Harper, M. J.,Houghton, L. A. (2016). High-Dose Monthly Maternal Cholecalciferol Supplementation during Breastfeeding Affects Maternal and Infant Vitamin D Status at 5 Months Postpartum: A Randomized Controlled Trial J Nutr, 146(10), 1999-2006 | Intervention/exposure vs comparator
596 | Wheeler, B. J.,Taylor, B. J.,Herbison, P.,Haszard, J. J.,Mikhail, A.,Jones, S.,Harper, M. J.,Houghton, L. A. (2017). Effect of high dose monthly maternal cholecalciferol supplementation during breastfeeding on infant and maternal vitamin d status at 5 months post-partum: a randomized controlled trial International journal of pediatric endocrinology, 2017(#issue#), #Pages# | Intervention/exposure vs comparator
597 | Wickens, K.,Barthow, C.,Mitchell, E. A.,Kang, J.,van Zyl, N.,Purdie, G.,Stanley, T.,Fitzharris, P.,Murphy, R.,Crane, J. (2018). Effects of Lactobacillus rhamnosus HN001 in early life on the cumulative prevalence of allergic disease to 11 years Pediatr Allergy Immunol, 29(8), 808-814 | Outcome
598 | Wicklow, B.,Gallo, S.,Majnemer, A.,Vanstone, C.,Comeau, K.,Jones, G.,L’Abbe, M.,Khamessan, A.,Sharma, A.,Weiler, H.,Rodd, C. (2016). Impact of Vitamin D Supplementation on Gross Motor Development of Healthy Term Infants: A Randomized Dose-Response Trial Phys Occup Ther Pediatr, 36(3), 330-42 | Intervention/exposure vs comparator
599 | Wojcicki, J. M.,Heyman, M. B.,Elwan, D.,Lin, J.,Blackburn, E.,Epel, E. (2016). Early exclusive breastfeeding is associated with longer telomeres in Latino preschool children Am J Clin Nutr, 104(2), 397-405 | Outcome
600 | Wong, V. C. H.,Maguire, J. L.,Omand, J. A.,Dai, D. W. H.,Lebovic, G.,Parkin, P. C.,O’Connor, D. L.,Birken, C. S.,Cohn, R.,Lau, E.,Laupacis, A.,Salter, M.,Szatmari, P.,Weir, S.,Anderson, L. N.,Borkhoff, C. M.,Keown-Stoneman, C.,Kowal, C.,Mason, D.,Abdurrahman, M.,Anderson, K.,Arbess, G.,Baker, J.,Barozzino, T.,Bergeron, S.,Bhagat, D.,Bloch, G.,Bonifacio, J.,Bowry, A.,Calpin, C.,Campbell, D.,Cheema, S.,Cheng, E.,Chisamore, B.,Constantin, E.,Danayan, K.,Das, P.,Derocher, M. B.,Do, A.,Doukas, K.,Egger, A.,Farber, A.,Freedman, A.,Freeman, S.,Gazeley, S.,Guiang, C.,Ha, D.,Handford, C.,Hanson, L.,Harrington, L.,Jacobson, S.,Jagiello, L.,Jansz, G.,Kadar, P.,Kim, F.,Kiran, T.,Knowles, H.,Kwok, B.,Lakhoo, S.,Lam-Antoniades, M.,Leduc, D.,Leung, F. H.,Li, A.,Li, P.,Malach, J.,Male, R.,Mascoll, V.,Meret, A.,Mok, E.,Moodie, R.,Nader, M.,Nash, K.,Naymark, S.,Owen, J.,Peer, M.,Pena, K.,Perlmutar, M.,Persaud, N.,Pinto, A.,Porepa, M.,Qi, V.,Ramji, N.,Ramji, N.,Raza, D.,Rosenthal, A.,Rouleau, K.,Ruderman, C.,Saunderson, J.,Schiralli, V.,Sgro, M.,Shuja, H.,Shepherd, S.,Smiltnieks, B.,Srikanthan, C.,Taylor, C.,Treherne, S.,Turner, S.,Uddin, F.,van den Heuvel, M.,Vaughan, J.,Weisdorf, T.,Wijayasinghe, S.,Wong, P.,Yaremko, J.,Ying, E.,Young, E.,Zajdman, M.,Bazeghi, F.,Bouchard, V.,Bustos, M.,Camacho, C.,Dalwadi, D.,Koroshegyi, C.,Malhi, T.,Thadani, S.,Thompson, J.,Thompson, L.,Aglipay, M.,Bayoumi, I.,Carsley, S.,Cost, K.,Eny, K.,Kim, T.,Kinlin, L.,Omand, J.,Vanderhout, S.,Vanderloo, L.,Allen, C.,Boodhoo, B.,Chan, O.,Hall, J.,Juni, P.,Pope, K.,Thorpe, K.,Kandel, R.,Rodrigues, M.,Vandenberghe, H. (2019). A Positive Association Between Dietary Intake of Higher Cow’s Milk-Fat Percentage and Non−High-Density Lipoprotein Cholesterol in Young Children Journal of Pediatrics, 211(#issue#), 105-111.e2 | Intervention/exposure vs comparator
601 | Woo, J. G.,Sucharew, H.,Su, W.,Khoury, P. R.,Daniels, S. R.,Kalkwarf, H. J. (2018). Infant Weight and Length Growth Trajectories Modeled Using Superimposition by Translation and Rotation Are Differentially Associated with Body Composition Components at 3 and 7 Years of Age J Pediatr, 196(#issue#), 182-188.e1 | Outcome
602 | Wopereis, H.,Sim, K.,Shaw, A.,Warner, J. O.,Knol, J.,Kroll, J. S. (2018). Intestinal microbiota in infants at high risk for allergy: Effects of prebiotics and role in eczema development J Allergy Clin Immunol, 141(4), 1334-1342.e5 | Outcome
603 | Wu, S. L.,Ding, D.,Fang, A. P.,Chen, P. Y.,Chen, S.,Jing, L. P.,Chen, Y. M.,Zhu, H. L. (2017). Growth, Gastrointestinal Tolerance and Stool Characteristics of Healthy Term Infants Fed an Infant Formula Containing Hydrolyzed Whey Protein (63%) and Intact Casein (37%): A Randomized Clinical Trial Nutrients, 9(11), #Pages# | Intervention/exposure vs comparator
604 | Wu, Y. Y.,Lye, S.,Briollais, L. (2017). The role of early life growth development, the FTO gene and exclusive breastfeeding on child BMI trajectories Int J Epidemiol, 46(5), 1512-1522 | Outcome
605 | Xinias, I.,Cassimos, D.,Trypsianis, G.,Nivatsi, M.,Mavroudi, A. (2019). Immediate vs delayed cow’s milk protein allergy in terms of tolerance at year 1 Annals of Allergy, Asthma and Immunology, 123(3), 304-306 | Participant health
606 | Yalaki, Z.,Ozmen, S.,Tasar, M. A.,Dallar, Y. (2016). The Serum Concentrations of Trace Elements and Vitamin A in Turkish Six-Month-Old Infants with Different Feeding Practices J Nutr Sci Vitaminol (Tokyo), 62(4), 235-239 | Study design
607 | Yang, M.,Tan, M.,Wu, J.,Chen, Z.,Long, X.,Zeng, Y.,Cai, H.,Zhang, Y.,Geng, L.,Xiao, Y.,Ke, H.,Liu, Y.,Rong, L.,Fu, S.,Wang, H.,Wang, Y.,Li, X.,Chen, P.,Li, K.,Xie, J.,Chen, H.,Li, H.,Wang, H.,Li, D. Y.,Gong, S. (2019). Prevalence, Characteristics, and Outcome of Cow’s Milk Protein Allergy in Chinese Infants: A Population-Based Survey JPEN J Parenter Enteral Nutr, 43(6), 803-808 | Intervention/exposure vs comparator
608 | Yang, S.,Martin, R. M.,Oken, E.,Hameza, M.,Doniger, G.,Amit, S.,Patel, R.,Thompson, J.,Rifas-Shiman, S. L.,Vilchuck, K.,Bogdanovich, N.,Kramer, M. S. (2018). Breastfeeding during infancy and neurocognitive function in adolescence: 16-year follow-up of the PROBIT cluster-randomized trial PLoS Med, 15(4), e1002554 | Outcome
609 | Yeiser, M.,Harris, C. L.,Kirchoff, A. L.,Patterson, A. C.,Wampler, J. L.,Zissman, E. N.,Berseth, C. L. (2016). Growth and tolerance of infants fed formula with a new algal source of docosahexaenoic acid: Double-blind, randomized, controlled trial Prostaglandins Leukot Essent Fatty Acids, 115(#issue#), 89-96 | Intervention/exposure vs comparator
610 | Yeung, H.,Leff, M.,Rhee, K. E. (2017). Effect of Exclusive Breastfeeding Among Overweight and Obese Mothers on Infant Weight-for-Length Percentile at 1 Year Breastfeed Med, 12(#issue#), 39-47 | Intervention/exposure vs comparator
611 | Yorulmaz, A.,Sert, S.,Yilmaz, F. H.,Kara, F.,Cinarlidere, S. (2018). The evaluation of primary school readiness levels of the children aged 66 - 72 months with the denver II test Iranian Journal of Pediatrics, 28(5), #Pages# | Study design
612 | Young, B. E.,Levek, C.,Reynolds, R. M.,Rudolph, M. C.,MacLean, P.,Hernandez, T. L.,Friedman, J. E.,Krebs, N. F. (2018). Bioactive components in human milk are differentially associated with rates of lean and fat mass deposition in infants of mothers with normal vs. elevated BMI Pediatr Obes, 13(10), 598-606 | Intervention/exposure vs comparator
613 | Zamora-Kapoor, A.,Omidpanah, A.,Nelson, L. A.,Kuo, A. A.,Harris, R.,Buchwald, D. S. (2017). Breastfeeding in Infancy Is Associated with Body Mass Index in Adolescence: A Retrospective Cohort Study Comparing American Indians/Alaska Natives and Non-Hispanic Whites J Acad Nutr Diet, 117(7), 1049-1056 | Outcome
614 | Zaragoza Cortes, J.,Trejo Osti, L. E.,Ocampo Torres, M.,Maldonado Vargas, L.,Ortiz Gress, A. A. (2018). Poor breastfeeding, complementary feeding and dietary diversity in children and their relationship with stunting in rural communities Nutr Hosp, 35(2), 271-278 | Study design
615 | Zavareh, M. S. A.,Hasani, M.,Darabi, M.,Mirzaei, A.,Khorshidi, A.,Saeidi, A.,Momeni, K.,Jalilian, M. (2018). Growth indicators and nutritional supplement evaluation in 6-12 months year old children’s: A perspective from Ilam Electronic Journal of General Medicine, 15(3), #Pages# | Study design, Intervention/exposure vs comparator
616 | Zhong, H.,Penders, J.,Shi, Z.,Ren, H.,Cai, K.,Fang, C.,Ding, Q.,Thijs, C.,Blaak, E. E.,Stehouwer, C. D. A.,Xu, X.,Yang, H.,Wang, J.,Wang, J.,Jonkers, Dmae,Masclee, A. A. M.,Brix, S.,Li, J.,Arts, I. C. W.,Kristiansen, K. (2019). Impact of early events and lifestyle on the gut microbiota and metabolic phenotypes in young school-age children Microbiome, 7(1), 2 | Outcome
617 | Zhu, Y.,Olsen, S. F.,Mendola, P.,Halldorsson, T. I.,Yeung, E. H.,Granstrom, C.,Bjerregaard, A. A.,Wu, J.,Rawal, S.,Chavarro, J. E.,Hu, F. B.,Zhang, C. (2017). Maternal dietary intakes of refined grains during pregnancy and growth through the first 7 y of life among children born to women with gestational diabetes Am J Clin Nutr, 106(1), 96-104 | Outcome
618 | Zhuang, J.,Bei, F.,Qin, Y.,Sun, J.,Wu, S. (2018). Effect of high sn-2 palmitate infant formula on the excretion of fatty acids, calcium and magnesium in infants Chinese journal of clinical nutrition, 26(4), 214-220 | Language
619 | Zielinska, M. A.,Hamulka, J.,Grabowicz-Chadrzynska, I.,Brys, J.,Wesolowska, A. (2019). Association between Breastmilk LC PUFA, Carotenoids and Psychomotor Development of Exclusively Breastfed Infants Int J Environ Res Public Health, 16(7), #Pages# | Intervention/exposure vs comparator
620 | (2016). Five-Year Follow-Up of High-Risk Infants with Family History of Allergy Who Were Exclusively Breast-Fed or Fed Partial Whey Hydrolysate, Soy, and Conventional Cow’s Milk Formulas: Expression of Serious Concern J Pediatr Gastroenterol Nutr, 63(2), 307 | Study design
621 | (2017). Breast really is best World of Irish Nursing & Midwifery, 25(5), 63-63 | Publication status
622 | (2017). Further evidence that breastfeeding reduces ill health Practising Midwife, 20(6), 1-2 | Publication status
623 | (2017). Relationship between growth and illness, enteropathogens and dietary intakes in the first 2 years of life: findings from the MAL-ED birth cohort study BMJ Glob Health, 2(4), e000370 | Intervention/exposure vs comparator Country
624 | (2018). Breastfeeding Prevents Diabetes Diabetes Self-Management, 35(5), 6-6 | Publication status
625 | (2018). The effects of feeding practices and appetitive traits on infant anthropometry in 6-month infants born to obese women-a secondary analysis of the UPBEAT trial Reproductive sciences (thousand oaks, calif.), Conference: 65th Annual Scientific Meeting of the Society for Gynecologic Investigation, SGI 2018. United States. 25(1), 268A | Publication status
626 | (2019). 310: association of breastfeeding (BF) and IQ American journal of obstetrics and gynecology, 220(1), S217-S218 | Publication status
627 | (2019). Coronary Syndrome, HPV Vaccination, Acute Sore Throat, Food Allergies, Breastfeeding Am Fam Physician, 99(12), 737 | Publication status, Study design

xiii Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xiv U.S. Food and Drug Administration. Version 19 December 2013. Internet: https://www.fda.gov/Food/GuidanceRegulation/GuidanceDocumentsRegulatoryInformation/InfantFormula/ucm136118.htm#manufacture (accessed March 23, 2018).

xv Food and Agriculture Organization of the United Nations. World Health Organization. Codex Alimentarius. International Food Standards. Standard for infant formula and formulas for special medical purposes intended for infants. Codex Stan 72-1981. 2007.

xvi The human development classification from the Pregnancy and Birth to 24 Months (P/B-24) Project, which was used to screen micronutrient status literature from the original literature search, was applied to the updated literature search for consistency. During the P/B-24 Project, the human development classification was the Human Development Index (HDI) ranking from the most recent Human Development Report ( United Nations Development Programme. Human Development Report 2014. New York, 2014. )

xvii During the Pregnancy and Birth to 24 Months (P/B-24) Project, systematic review questions were defined to examine the relationships between human milk and infant formula consumption and several outcomes, and NESR used a single literature search to identify potential studies for the family of reviews (https://nesr.usda.gov/infant-milk-feeding-practices-technical-expert-collaborative). Some of the intended reviews, including nutrient status, were not completed before the end of the Project. The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee, used and updated the literature search and screening underway from the P/B-24 Project according to the inclusion and exclusion criteria described herein.

xviii After conducting the search, the librarian used the citation manager to screen out search results from Embase, CINAHL, and Cochrane with the following keywords in the title: (aids AND “Acquired Immunodeficiency Syndrome”) OR hiv OR HIV/AIDS OR human immunodefic* OR Acquired Immunodefic* OR “low birth weight” OR lbw OR vlbw OR elbw OR pcb OR pcbs OR Polychlorinated Biphenyl* OR Polychlorobiphenyl Compound* OR dioxin* OR (breast AND (tumor* OR tumour* OR cancer* OR carcinoma* OR disease*)) OR preterm OR premature

xix During the Pregnancy and Birth to 24 Months (P/B-24) Project, systematic review questions were defined to examine the relationships between human milk and infant formula consumption and several outcomes, and NESR used a single literature search to identify potential studies for the family of reviews (https://nesr.usda.gov/infant-milk-feeding-practices-technical-expert-collaborative). Some of the intended reviews, including micronutrient status, were not completed before the end of the Project. The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee, used and updated the literature search and screening underway from the P/B-24 Project according to the inclusion and exclusion criteria described herein.

xx The number of records the literature yielded prior to the removal of duplicates is unavailable.

xxi During the Pregnancy and Birth to 24 Months (P/B-24) Project, systematic review questions were defined to examine the relationships between human milk and infant formula consumption and several outcomes, and NESR used a single literature search to identify potential studies for the family of reviews (https://nesr.usda.gov/infant-milk-feeding-practices-technical-expert-collaborative). Some of the intended reviews, including micronutrient status, were not completed before the end of the Project. The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee, used and updated the literature search and screening underway from the P/B-24 Project according to the inclusion and exclusion criteria described herein.