# WHAT IS THE RELATIONSHIP BETWEEN THE DURATION, FREQUENCY, AND VOLUME OF EXCLUSIVE HUMAN MILK AND/OR INFANT FORMULA CONSUMPTION AND NUTRIENT STATUS?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and nutrient status?

### What is the answer to the question?

- Moderate evidence indicates that ever, compared with never, consuming human milk may be associated with fatty acid status from birth to 24 months. However, the difference in fatty acid status between infants fed human milk and infants fed infant formula is likely to depend on the composition of the human milk and infant formula consumed. Insufficient evidence is available to determine the relationship between ever, compared with never, consuming human milk and iron and zinc status from birth to 24 months. No evidence is available to determine the relationship between ever, compared with never, consuming human milk and iodine, vitamin B12, and vitamin D status from birth to 24 months.
- Insufficient evidence is available to determine the relationship between the duration of any human milk consumption, among infants fed human milk, and iron, zinc, vitamin D, and fatty acid status from birth to 24 months. No evidence is available to determine the relationship between the duration of any human milk consumption, among infants fed human milk, and iodine or vitamin B12 status from birth to 24 months.
- Insufficient evidence is available to determine the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and fatty acid status. No evidence is available to determine the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and iron, zinc, iodine, vitamin B12, or vitamin D status from birth to 24 months.
- No evidence is available to determine the relationship between the intensity, proportion, or amount of human milk consumed by mixed-fed infants and iron, zinc, iodine, vitamin B12, vitamin D, or fatty acid status from birth to 24 months.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee, conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- The population of interest was generally health infants and toddlers (birth to 24 months).

### What evidence was found?

- This review includes 23 articles.
- The review examined available evidence about:
  ○ Infants who ever consumed milk (i.e., any amount of human milk) compared with infants who never consumed human milk,
  ○ Infants who consumed human milk (i.e., any amount of human milk) for different durations,
  ○ Infants who consumed human milk exclusively for different durations before infant formula was added to their diets, and
  ○ Mixed-fed infants (i.e., consuming both human milk and infant formula, but not complementary foods and beverages) who consumed different amounts of human milk.
- These articles examined available evidence related to iron, zinc, iodine, vitamin D, vitamin B12, and fatty acid status.
- Most evidence compared fatty acid status between infants who ever and never consumed human milk. Infants who ever consume human milk and infants who never consume human milk (i.e., formula-fed infants) may have differences in fatty acid status. The difference in fatty acid status probably depends on infant formula ingredients and human milk composition.
- There are limitations in the evidence as follows:
  ○ There was not a lot of evidence about infants who consumed human milk for different durations, infants who consumed human milk exclusively for different durations before infant formula was added to their diets, iron status, zinc status, and vitamin D status. There was no evidence about mixed-fed infants who consumed different amounts of human milk, iodine status, and vitamin B12 status.
  ○ Most studies were designed to examine the effect of new infant formula ingredients and not the systematic review question.
  ○ Some of the infant formulas used in the studies may be different from infant formulas currently sold in the United States.
  ○ It is possible for factors other than infant feeding to impact the outcomes, and these factors were addressed differently by different studies.

### How up-to-date is this systematic review?

This review searched for studies from January, 1980 to September, 2019.

## FULL REVIEW

### Systematic review question

What is the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and nutrient status?

### Conclusion statements and grades

#### Ever vs never consuming human milk

Moderate evidence indicates that ever, compared with never, consuming human milk may be associated with fatty acid status from birth to 24 months. However, the difference in fatty acid status between infants fed human milk and infants fed infant formula is likely to depend on the composition of the human milk and infant formula consumed. (Grade: Moderate)

Insufficient evidence is available to determine the relationship between ever, compared with never, consuming human milk and iron and zinc status from birth to 24 months. No evidence is available to determine the relationship between ever, compared with never, consuming human milk and iodine, vitamin B12, and vitamin D status from birth to 24 months. (Grade: Grade not assignable)

#### Duration of any human milk consumption among infants fed human milk

Insufficient evidence is available to determine the relationship between the duration of any human milk consumption, among infants fed human milk, and iron, zinc, vitamin D, and fatty acid status from birth to 24 months. No evidence is available to determine the relationship between the duration of any human milk consumption, among infants fed human milk, and iodine or vitamin B12 status from birth to 24 months. (Grade: Grade not assignable)

#### Duration of exclusive human milk consumption before the introduction of infant formula

Insufficient evidence is available to determine the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and fatty acid status. No evidence is available to determine the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and iron, zinc, iodine, vitamin B12, or vitamin D status from birth to 24 months. (Grade: Grade not assignable)

#### Intensity, proportion, or amount of human milk consumed by mixed-fed infants

No evidence is available to determine the relationship between the intensity, proportion, or amount of human milk consumed by mixed-fed infants and iron, zinc, iodine, vitamin B12, vitamin D, or fatty acid status from birth to 24 months. (Grade: Grade not assignable)

### Summary of the evidence

- This systematic review examines the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and nutrient status. Specifically, this systematic review examines available evidence that compares:
  ○ Infants who ever consumed milk (i.e., any amount of human milk) with infants who never consumed human milk,
  ○ Infants who consumed human milk (i.e., any amount of human milk) for different durations,
  ○ Infants who consumed human milk exclusively for different durations before the introduction of infant formula, and
  ○ Mixed-fed infants (i.e., consuming both human milk and infant formula, but not complementary foods and beverages) who consumed different intensities, proportions, or amounts of human milk.
- Human milk refers to mother’s own milk provided at the breast (i.e., nursing) or expressed and fed fresh or after refrigeration or freezing. Examinations of donor milk are not included in this review. Exclusive human milk consumption refers to consuming human milk alone and not in combination with infant formula or complementary foods and beverages. Infant formula refers to commercially prepared infant formula meeting the FDA and/or Codex Alimentarius international food standards. Complementary foods and beverages are foods and beverages other than human milk or infant formula (liquids, semisolids, and solids) provided to an infant or young child to provide nutrients and energy.
- The outcomes of interest were iron status (including iron deficiency and anemia), zinc status, iodine status, vitamin B12 status, vitamin D status, and fatty acid status.
- This review identified 23 articles.^1–23^
  ○ [underlined: Iron status]: Ten articles, published between 1990 and 2019, examined the relationships of (a) ever, compared with never, consuming human milk, and (b) different durations of any human milk consumption, among infants fed human milk, with iron status from birth to 24 months.
    (c) The evidence available from 2 studies did not show a consistent association between ever, compared with never, consuming human milk and anemia. The evidence available from 5 studies did not show consistent associations between ever, compared with never, consuming human milk and hemoglobin, hematocrit, red blood cell count, mean corpuscular volume, red cell distribution width, serum ferritin, or serum iron.
    (d) The evidence available from 3 studies did not show a consistent association between the duration of any human milk consumption, among infants fed human milk, and iron deficiency or anemia. The evidence available from 4 studies did not show consistent associations between the duration of any human milk consumption, among infants fed human milk, and hemoglobin, hematocrit, serum ferritin, serum iron, mean corpuscular volume, transferrin receptor, or transferrin saturation.
  ○ [underlined: Zinc status]: Five articles, published between 1986 and 1994, examined the relationships of (a) ever, compared with never, consuming human milk, and (b) different durations of any human milk consumption, among infants fed human milk, with zinc status from birth to 24 months.
    (c) The evidence available from 4 studies did not show a consistent association between ever, compared with never, consuming human milk and zinc status.
    (d) The evidence available from 2 studies was insufficient to determine whether there is an association between the duration of any human milk consumption, among infants fed human milk, and zinc status.
  ○ [underlined: Vitamin D status]: One article, published in 2014, examined the relationship between the duration of any human milk consumption, among infants fed human milk, and vitamin D status from birth to 24 months. This evidence was insufficient to determine whether there is an association between the duration of any human milk consumption, among infants fed human milk, and vitamin D status.
  ○ [underlined: Fatty acid status]: Nine articles, published between 1986 and 2016, examined the relationships of (a) ever, compared with never, consuming human milk, (b) different durations of any human milk consumption, among infants fed human milk, and (c) different durations of exclusive human milk consumption before the introduction of infant formula with fatty acid status from birth to 24 months.
    (a) The evidence available from 7 studies was moderately consistent in showing that ever, compared with never, consuming human milk is related to fatty acid status, but the direction and strength of associations can vary depending on the composition of the infant formula fed to participants who never consumed human milk (and also likely due to the composition of human milk, although this could not be assessed), as well as the specific types of fatty acids examined in the blood.
    (b) The evidence available from 1 study was insufficient to determine whether an association exists between the duration of any human milk consumption, among infants fed human milk, and fatty acid status.
    (c) The evidence available from 1 study was insufficient to determine whether an association exists between the duration of exclusive human milk consumption before the introduction of infant formula and fatty acid status.
  ○ No studies met the inclusion criteria that examined iodine status or vitamin B12 status.
- The ability to draw stronger conclusions was primarily limited by:
  ○ The small number of studies that presented evidence on each topic,
  ○ The study designs, as most studies were designed to examine the effect of novel infant formula compositions rather than differences in outcomes between infants ever and never fed human milk,
  ○ Concerns about the generalizability of the evidence to U.S. infants consuming infant formulas currently on the market, and
  ○ Concerns about the potential for bias, especially bias due to confounding.

### Iron status

Ten articles, published between 1990 and 2019, examined the relationships of ever compared with never consuming human milk, and different durations of any human milk consumption, with iron status from birth to 24 months.^1–3,7–9,12,16,20,23^

No evidence was identified that met the inclusion criteria to examine different durations of exclusive human milk consumption before the introduction of infant formula or different intensities, proportions, or amounts of human milk consumed by mixed-fed infants.

#### Description of the evidence comparing ever with never consuming human milk (Table 1)

Six articles presented evidence comparing the iron status of infants who ever consumed human milk with that of infants who never consumed human milk.^1–3,9,12,23^

##### Population

The samples of infants were from the United States, China, Germany, and Japan. Five studies followed participants starting at or close to their birth^1,2,9,12,23^ and one followed participants starting at 12 months.^3^ Participants in the study by Cusick et al^3^ were from low-income U.S. families with diverse racial and ethnic backgrounds. Participants from a second U.S.-based study were mostly White.^2^ Authors of the remaining 4 studies did not report the racial or ethnic composition of their samples.

##### Interventions/exposures and comparators

Infants who consumed human milk:

- Four studies included a group of infants fed human milk exclusively.^1,9,12,23^ Wu et al^23^ and Jochum et al^9^ specified that infants were only fed human milk throughout the observation period (i.e., 8 weeks and 4 months, respectively). The other studies did not specify the duration of the exclusive human milk-feeding period.
- Three studies included a group of infants fed human milk, but not exclusively. Amano and Murakami^1^ included a group described as partially breastfed, and Cusick et al^3^ included a group described as ever breastfed. Bradley et al^2^ identified 3 groups of human milk-fed infants. One group was fed human milk ≥6 months with up to 1 supplemental feeding per day of a low-iron formula. The other 2 groups consumed human milk for 1 to 8 weeks and were then randomized to consume formulas with different levels of iron.

Infants who never consumed human milk:

- In 3 studies, parents who decided to formula-feed selected the formula.^1,3,9^ Jochum et al^9^ stated that families with no history of atopic disease chose 1 of 11 different cow milk formulas, whereas study staff recommended partially hydrolyzed whey protein formula to parents of children with a family history of atopy. Authors of the other 2 studies did not specify the formulas parents selected.
- In 3 studies, parents who decided to formula-feed were assigned to a formula by research staff.^2,12,23^ Wu et al^23^ assigned a standard infant formula with iron, whereas Bradley et al^2^ and Lönnerdal and Chen^12^ randomly allocated infants to formulas with different levels of iron and different levels and sources of protein, respectively.

In addition to human milk and infant formula, some infants consumed complementary foods and beverages and/or iron supplements prior to the measurement of iron status.

- In the study by Bradley et al,^2^ infants could consume complementary foods and beverages, including iron-fortified cereals, starting at 4 months (i.e., prior to the outcome measures at 6 and 12 months). Mineral supplements were not prescribed to any of the infants.
- In the study by Amano and Murakami,^1^ infants could consume complementary foods and beverages prior to the outcome measures at 6-7 and 9-10 months. In addition, infants determined to have anemia at the 6-7 month time point were treated and omitted from the 9-10 month analyses.
- Lönnerdal and Chen^12^ and Cusick et al^3^ did not report whether infants received complementary foods and beverages prior to the measurement of outcomes. Lönnerdal and Chen^12^ did not specify which outcome age they reported (i.e., 2, 4, 8, or 12 weeks), however Cusick et al^3^ measured outcomes at 12 and 24 months so it is likely that participants were consuming complementary foods and beverages.
- Lönnerdal and Chen,^12^ Wu et al,^23^ and Cusick et al^3^ did not report whether infants received iron supplements prior to measurement of the outcomes, nor did they provide information about whether therapeutic iron was taken by infants with low iron status at earlier time points preceding iron status measurements at later time points.

##### Outcomes

Two studies examined anemia. Amano and Murakami^1^ reported anemia at 9-10 months, defined as hemoglobin <11.0 g/dL, among infants who did not have anemia at 6-7 months. Cusick et al^3^ reported incident anemia at 24 months, defined as anemia at 24 months among children who did not have anemia at 12 months, and persistent anemia at 24 months, defined as anemia at 24 months among children who also had anemia at 12 months. Anemia was defined as hemoglobin <11.0 g/dL adjusted for altitude.

Five studies^1,2,9,12,23^ examined iron indicators, including hemoglobin, hematocrit, red blood cell count, mean corpuscular volume, red cell distribution width, serum ferritin, and serum iron measured between the ages 4 weeks to 12 months.

#### Synthesis and assessment^ii^ of the evidence comparing ever with never consuming human milk (Table 1)

The evidence examining the association between ever, compared with never, consuming human milk and iron status is inconclusive. In the synthesis and assessment of the evidence that follows, several limitations are described that make it difficult to draw a conclusion.

Consistency: The evidence has limited consistency.

- [underlined: Anemia]: The evidence available from 2 studies did not show a consistent association between never, compared with ever, consuming human milk and anemia. The studies reported statistically significant findings in opposite directions and with different magnitudes of effect.
  ○ Amano and Murakami^1^ found that formula-fed infants had significantly lower odds of anemia at 9-10 months than infants fed human milk exclusively for an unreported duration [OR 0.072 (95% CI: 0.024, 0.222)]. Cusick et al^3^ found that infants who never consumed human milk had significantly higher odds of incident anemia and persistent anemia at 24 months than infants who ever consumed human milk [OR 1.06 (95% CI: 1.04, 1.06) and OR 1.07 (95% CI: 1.03, 1.11), respectively].
  ○ This inconsistency may be due to key differences between these studies.
    ■ Cusick et al^3^ studied more than half a million (N=583,149) racially and ethnically diverse low-income 12- to 24-month-old infants in the United States. Amano and Murakami^1^ studied a much smaller group of infants in Japan (N<286; the number of infants included in the analysis of interest was not reported) from birth to 9-10 months.
    ■ Cusick et al^3^ compared infants who never consumed human milk with infants who ever consumed human milk. The authors did not define ever, but presumably, some of the infants in this group were also fed with infant formula. Amano and Murakami,^1^ on the other hand, compared infants whose parents chose to formula feed from birth with infants whose parents chose to feed human milk exclusively for an unreported period of time.
    ■ Amano and Murakami^1^ assessed anemia at 9-10 months and restricted the analysis to infants who did not have anemia at 6-7 months. Cusick et al^3^ assessed incident anemia at 24 months (i.e., anemia at 24 months among children who did not have anemia at 12 months) as well as persistent anemia at 24 months (i.e., anemia at 24 months among children who also had anemia at 12 months). It is unlikely that all cases of persistent anemia were captured, however, because infants with a follow-up earlier than 24 months were excluded from the study, and infants with anemia at 12 months were more likely to have a follow-up earlier than 24 months than infants without anemia at 12 months.
    ■ Amano and Murakami^1^ controlled for sex, delivery method, gestational age, birthweight, weight gain from birth to 9-10 months, “daily food intake” (undefined), phototherapy for jaundice, and maternal anemia, while Cusick et al^3^ controlled for sex, race, birthweight, and height- and weight-for-age percentile categories at 12 months.
- [underlined: Other iron status outcomes]: The evidence available from 5 studies did not show a consistent association between never, compared with ever, consuming human milk and other iron status outcomes.
  ○ Amano and Murakami^1^ found that infants who consumed human milk exclusively for an unreported duration of time tended to have lower mean hemoglobin, hematocrit, and mean corpuscular volume, and higher red cell distribution width at 6-7 months and at 9-10 months (among infants who did not have anemia at 6-7 months) than infants who consumed formula. However, this study did not find similar associations when the exposure variable was partial (rather than exclusive) human milk consumption.
  ○ The remaining 4 studies reported nonsignificant associations for almost all analyses examining comparisons of ever with never consuming human milk and indicators of iron status from 4 weeks to 12 months.^1,2,9,12,23^
  ○ Limitations of the body of evidence make it difficult to interpret these findings. The nonsignificant findings may be the result of underpowered analyses; none of the studies reported statistical power for the analyses of interest, and some group sizes were small. In addition, Lönnerdal and Chen^12^ did not report infants’ age at the time of the outcome measure, and Wu et al^23^ did not report the name/units of the iron indicator measured.

Precision: The evidence has limited precision.

- The body of evidence may have a limited number of sufficiently powered studies.
  ○ The studies that examined anemia were sufficiently powered; however, the reported findings lacked precision because they were inconsistent in the direction and magnitude of the associations.
  ○ As previously described, there is not enough information to determine whether the studies that examined other iron status outcomes had sufficient statistical power to examine the relationships of interest. In addition, there were only 5 studies.

Directness: The evidence has moderate directness.

- Four of the 6 articles reported study objectives that included the comparison of iron status between human milk-fed and formula-fed infants.^1–3,23^

Generalizability: The evidence has limited generalizability.

- Anemia was examined at 9-10 and 12-24 months, and not throughout the birth to 24 month period. The studies that examined anemia only included infants from Japan^1^ and low-income infants from the United States.^3^ The results from the Japanese study may lack generalizability to the U.S. population for a couple of reasons. First, the study authors state that, in Japan, infants are typically fed homemade baby food, whereas many American infants are fed iron-fortified complementary foods. Second, the average birthweight in the Japanese sample was about 3 kg, which is equivalent to only about the 25^th^ percentile on the World Health Organization growth curves used in the United States.^iii^ In the study by Cusick et al,^3^ the persistent anemia findings may not be representative of infants with persistent anemia (i.e., anemia at 12 and 24 months) because infants with a follow-up prior to 24 months were excluded, yet infants with anemia at 12 months were more likely than infants without anemia at 12 months to have a follow-up earlier than 24 months.
- Other iron status outcomes were examined from 4 weeks to 12 months. Infants in the study by Bradley et al^2^ were mostly White, and the remaining studies did not report race or ethnicity.

Risk of bias: There is a limited likelihood that the design and conduct of the studies have prevented or minimized bias.

- None of the studies accounted for all of the key confounders listed on the analytic framework. Notably, the accounting for complementary feeding, which could have provided a meaningful contribution towards some participants’ iron status, was poor. Amano and Murakami^1^ controlled for “daily food intake” but did not adequately describe the variable, and 3 studies did not account for complementary feeding at all.^2,3,12^ In addition, no studies accounted for any of the other factors to be considered from the analytic framework, and the timing of cord clamping, in particular, may have an important confounding effect on anemia outcomes.^iv^
- The studies were prone to other risks of bias (Tables 2 and 3), which varied between studies.

Table 1 Evidence examining the relationship between ever vs never consuming human milk and iron status^*^

Article; Study design; Country | Ever vs never consuming human milk exposure^†^ | Iron status outcome^‡^ | Significant associations | Nonsignificant associations
Amano 2019 ^1^; RCS; Japan | EBF (ref) vs FF | Anemia (OR (95% CI)) @ 9-10 mo (N=NR) | 0.072 (0.024, 0.222); p<0.001
| EBF vs FF | RBC (mean ± SD, number*10^6^/μL) @ 6-7 mo in female subsample (N=109, 27) | . | 4.38 ± 0.33 vs 4.38 ± 0.25; NS
| | RBC (mean ± SD, number*10^6^/μL) @ 6-7 mo in male subsample (N=123, 27) | . | 4.53 ± 0.36 vs 4.52 ± 0.24; NS
| | RBC (mean ± SD, number*10^6^/μL) @ 9-10 mo in female subsample (N=NR) | . | 4.40 ± 0.34 vs 4.36 ± 0.29; NS
| | RBC (mean ± SD, number*10^6^/μL) @ 9-10 mo in male subsample (N=NR) | . | 4.46 ± 0.39 vs 4.45 ± 0.31; NS
| | Hb (mean ± SD, g/dL) @ 6-7 mo in female subsample (N=109, 27) | 11.5 ± 0.9 vs 12.0 ± 0.8; p<0.05 | .
| | Hb (mean ± SD, g/dL) @ 6-7 mo in male subsample (N=123, 27) | 11.3 ± 1.0 vs 12.1 ± 0.6; p<0.001 | .
| | Hb (mean ± SD, g/dL) @ 9-10 mo in female subsample (N=NR) | 11.3 ± 0.9 vs 12.0 ± 0.8; p<0.01 | .
| | Hb (mean ± SD, g/dL) @ 9-10 mo in male subsample (N=NR) | 10.9 ± 1.2 vs 12.2 ± 0.9; p<0.001 | .
| | Hct (mean ± SD, %) @ 6-7 mo in female subsample (N=109, 27) | . | 33.9 ± 2.6 vs 35.0 ± 2.2; NS
| | Hct (mean ± SD, %) @ 6-7 mo in male subsample (N=123, 27) | 33.7 ± 2.8 vs 35.7 ± 1.8; p<0.001 | .
| | Hct (mean ± SD, %) @ 9-10 mo in female subsample (N=NR) | . | 33.7 ± 2.6 vs 35.1 ± 2.5; NS
| | Hct (mean ± SD, %) @ 9-10 mo in male subsample (N=NR) | 73.1 ± 5.0 vs 79.7 ± 2.0; p<0.001^§^ | .
| | MCV (mean ± SD, fL) @ 6-7 mo in female subsample (N=109, 27) | 77.5 ± 3.9 vs 80.1 ± 3.1; p<0.01 | .
| | MCV (mean ± SD, fL) @ 6-7 mo in male subsample (N=123, 27) | 74.6 ± 4.4 vs 79.0 ± 2.3; p<0.001 | .
| | MCV (mean ± SD, fL) @ 9-10 mo in female subsample (N=NR) | 76.5 ± 4.6 vs 80.9 ± 3.3; p<0.001 | .
| | MCV (mean ± SD, fL) @ 9-10 mo in male subsample (N=NR) | 74.6 ± 4.4 vs 79.0 ± 2.3; p<0.001 | .
| | RDW (mean ± SD, %) @ 6-7 mo female subsample (N=109, 27) | . | 13.4 ± 0.6 vs 13.0 ± 0.7; NS
| | RDW (mean ± SD, %) @ 6-7 mo male subsample (N=123, 27) | 13.7 ± 0.8 vs 13.3 ± 0.6; p<0.05 | .
| | RDW (mean ± SD, %) @ 9-10 mo in female subsample (N=NR) | 13.5 ± 0.8 vs 13.0 ± 0.5; p<0.01 | .
| | RDW (mean ± SD, %) @ 9-10 mo in male subsample (N=NR) | 13.7 ± 0.9 vs 13.0 ± 0.8; p<0.001 | .
| Partial BF vs FF | RBC (mean ± SD, number*10^6^/μL) @ 6-7 mo in female subsample (N=47, 27) | . | 4.40 ± 0.32 vs 4.38 ± 0.25; NS
| | RBC (mean ± SD, number*10^6^/μL) @ 6-7 mo in male subsample (N=55, 27) | . | 4.52 ± 0.31 vs 4.52 ± 0.24; NS
| | RBC (mean ± SD, number*10^6^/μL) @ 9-10 mo in female subsample (N=NR) | . | 4.36 ± 0.34 vs 4.36 ± 0.29; NS
| | RBC (mean ± SD, number*10^6^/μL) @ 9-10 mo in male subsample (N=NR) | . | 4.50 ± 0.34 vs 4.45 ± 0.31; NS
| | Hb (mean ± SD, g/dL) @ 6-7 mo in female subsample (N=47, 27) | . | 11.8 ± 0.8 vs 12.0 ± 0.8; NS
| | Hb (mean ± SD, g/dL) @ 6-7 mo in male subsample (N=55, 27) | . | 11.9 ± 0.8 vs 12.1 ± 0.6; NS
| | Hb (mean ± SD, g/dL) @ 9-10 mo in female subsample (N=NR) | . | 11.8 ± 1.0 vs 12.0 ± 0.8; NS
| | Hb (mean ± SD, g/dL) @ 9-10 mo in male subsample (N=NR) | . | 12.0 ± 0.9 vs 12.2 ± 0.9; NS
| | Hct (mean ± SD, %) @ 6-7 mo in female subsample (N=47, 27) | . | 34.7 ± 2.5 vs 35.0 ± 2.2; NS
| | Hct (mean ± SD, %) @ 6-7 mo in male subsample (N=55, 27) | . | 34.9 ± 2.4 vs 35.7 ± 1.8; NS
| | Hct (mean ± SD, %) @ 9-10 mo in female subsample (N=NR) | . | 34.5 ± 2.9 vs 35.1 ± 2.5; NS
| | Hct (mean ± SD, %) @ 9-10 mo in male subsample (N=NR) | . | 78.2 ± 3.4 vs 79.7 ± 2.0; NS^§^
| | MCV (mean ± SD, fL) @ 6-7 mo in female subsample (N=47, 27) | . | 79.0 ± 3.2 vs 80.1 ± 3.1; NS
| | MCV (mean ± SD, fL) @ 6-7 mo in male subsample (N=55, 27) | . | 77.3 ± 2.9 vs 79.0 ± 2.3; NS
| | MCV (mean ± SD, fL) @ 9-10 mo in female subsample (N=NR) | . | 79.3 ± 3.3 vs 80.9 ± 3.3; NS
| | MCV (mean ± SD, fL) @ 9-10 mo in male subsample (N=NR) | . | 77.3 ± 2.9 vs 79.0 ± 2.3; NS
| | RDW (mean ± SD, %) @ 6-7 mo in female subsample (N=47, 27) | 13.4 ± 0.7 vs 13.0 ± 0.7; p<0.05 | .
| | RDW (mean ± SD, %) @ 6-7 mo in male subsample (N=55, 27) | . | 13.3 ± 0.7 vs 13.3 ± 0.6; NS
| | RDW (mean ± SD, %) @ 9-10 mo in female subsample (N=NR) | . | 13.3 ± 0.7 vs 13.0 ± 0.5; NS
| | RDW (mean ± SD, %) @ 9-10 mo in male subsample (N=NR) | . | 13.2 ± 0.7 vs 13.0 ± 0.8; NS
Bradley 1993 ^2^; NRCT; U.S. | High-Fe FF vs BF ≥6 mo | Hb (mean ± SD, g/dL) @ 6 mo (N=41, 37) | . | 12.0 ± 1.0 vs 11.8 ± 1.4; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=28, 37) | . | 12.2 ± 1.1 vs 12.1 ± 1.0; NS
| | Hct (mean ± SD, %) @ 6 mo (N=41, 36) | . | 35 ± 3 vs 35 ± 3; NS
| | Hct (mean ± SD, %) @ 12 mo (N=26, 37) | . | 36 ± 3 vs 36 ± 2; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=33, 31) | . | 39 ± 30 vs 45 ± 43; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=22, 30) | 31 ± 17 vs 23 ± 28; p<0.008 | .
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=28, 16) | . | 141 ± 54 vs 119 ± 75; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=18, 16) | . | 129 ± 65 vs 168 ± 105; NS
| High-Fe FF vs BF 1-8 wk then High-Fe FF | Hb (mean ± SD, g/dL) @ 6 mo (N=41, 26) | . | 12.0 ± 1.0 vs 11.3 ± 0.7; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=28, 21) | . | 12.2 ± 1.1 vs 11.7 ± 1.1; NS
| | Hct (mean ± SD, %) @ 6 mo (N=41, 25) | . | 35 ± 3 vs 33 ± 2; NS
| | Hct (mean ± SD, %) @ 12 mo (N=26, 20) | . | 36 ± 3 vs 34 ± 2; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=33, 26) | . | 39 ± 30 vs 40 ± 18; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=22, 21) | . | 31 ± 17 vs 31 ± 23; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=28, 24) | . | 141 ± 54 vs 108 ± 51; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=18, 19) | . | 129 ± 65 vs 106 ± 58; NS
| High-Fe FF vs BF 1-8 wk then Low-Fe FF | Hb (mean ± SD, g/dL) @ 6 mo (N=41, 21) | . | 12.0 ± 1.0 vs 11.5 ± 0.8; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=28, 20) | . | 12.2 ± 1.1 vs 11.9 ± 1.0; NS
| | Hct (mean ± SD, %) @ 6 mo (N=41, 21) | . | 35 ± 3 vs 34 ± 3; NS
| | Hct (mean ± SD, %) @ 12 mo (N=26, 20) | . | 36 ± 3 vs 35 ± 3; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=33, 22) | . | 39 ± 30 vs 29 ± 28; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=22, 19) | . | 31 ± 17 vs 24 ± 22; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=28, 19) | . | 141 ± 54 vs 113 ± 52; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=18, 16) | . | 129 ± 65 vs 109 ± 35; NS
| Low-Fe FF vs BF ≥6 mo | Hb (mean ± SD, g/dL) @ 6 mo (N=41, 37) | . | 11.8 ± 1.2 vs 11.8 ± 1.4; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=34, 37) | . | 12.2 ± 1.1 vs 12.1 ± 1.0; NS
| | Hct (mean ± SD, %) @ 6 mo (N=40, 36) | . | 35 ± 3 vs 35 ± 3; NS
| | Hct (mean ± SD, %) @ 12 mo (N=34, 37) | . | 36 ± 2 vs 36 ± 2; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=31, 31) | . | 31 ± 19 vs 45 ± 43; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=27, 30) | . | 18 ± 11 vs 23 ± 28; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=27, 16) | . | 117 ± 43 vs 119 ± 75; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=16, 16) | . | 122 ± 55 vs 168 ± 105; NS
| Low-Fe FF vs BF 1-8 wk then High-Fe FF | Hb (mean ± SD, g/dL) @ 6 mo (N=41, 26) | . | 11.8 ± 1.2 vs 11.3 ± 0.7; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=34, 21) | . | 12.2 ± 1.1 vs 11.7 ± 1.1; NS
| | Hct (mean ± SD, %) @ 6 mo (N=40, 25) | . | 35 ± 3 vs 33 ± 2; NS
| | Hct (mean ± SD, %) @ 12 mo (N=34, 20) | . | 36 ± 2 vs 34 ± 2; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=31, 26) | . | 31 ± 19 vs 40 ± 18; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=27, 21) | . | 18 ± 11 vs 31 ± 23; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=27, 24) | . | 117 ± 43 vs 108 ± 51; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=16, 19) | . | 122 ± 55 vs 106 ± 58; NS
| Low-Fe FF vs BF 1-8 wk then Low-Fe FF | Hb (mean ± SD, g/dL) @ 6 mo (N=41, 21) | . | 11.8 ± 1.2 vs 11.5 ± 0.8; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=34, 20) | . | 12.2 ± 1.1 vs 11.9 ± 1.0; NS
| | Hct (mean ± SD, %) @ 6 mo (N=40, 21) | . | 35 ± 3 vs 34 ± 3; NS
| | Hct (mean ± SD, %) @ 12 mo (N=34, 20) | . | 36 ± 2 vs 35 ± 3; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=31, 22) | . | 31 ± 19 vs 29 ± 28; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=27, 19) | . | 18 ± 11 vs 24 ± 22; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=27, 19) | . | 117 ± 43 vs 113 ± 52; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=16, 16) | . | 122 ± 55 vs 109 ± 35; NS
Cusick 2007 ^3^; RCS; U.S. | Ever BF (ref) vs never BF | Incident anemia (OR (95% CI)) @24 ± 4 mo (N=NR, NR) | 1.06 (1.04, 1.08) | .
| | Persistent anemia (OR (95% CI)) @24 ± 4 mo (N=NR, NR) | 1.07 (1.03, 1.11) | .
Jochum 1995 ^9^; PCS; Germany | EBF vs cow milk F | Hct (mean ± SE, %) @ 4 mo (N=50, 44) | . | 36.4 ± 3.0 vs 35.9 ± 2.7; NS
| | Hb (mean ± SE, g/dL) @ 4 mo (N=50, 44) | . | 12.1 ± 0.9 vs 11.9 ± 2.7; NS
| | Erythrocytes (mean ± SE, pL) @ 4 mo (N=50, 44) | . | 4.4 ± 0.4 vs 4.3 ± 0.3; NS
| | MCV (mean ± SE, fL) @ 4 mo (N=50, 44) | . | 81.9 ± 7.3 vs 84.1 ± 5.4; NS
| EBF vs partially hydrolyzed whey protein FF | Hct (mean ± SE, %) @ 4 mo (N=50, 35) | . | 36.4 ± 3.0 vs 35.3 ± 3.2; NS
| | Hb (mean ± SE, g/dL) @ 4 mo (N=50, 35) | . | 12.1 ± 0.9 vs 11.9 ± 1.0; NS
| | Erythrocytes (mean ± SE, pL) @ 4 mo (N=50, 35) | . | 4.4 ± 0.4 vs 4.2 ± 0.4; NS
| | MCV (mean ± SE, fL) @ 4 mo (N=50, 35) | . | 81.9 ± 7.3 vs 83.9 ± 4.0; NS
Lönnerdal 1990 ^12^; NRCT; China | EBF vs 1.4 g/dL protein and 55:45 whey:casein ratio FF | Hb (mean ± SD/SE, g/dl) @ time NR ≤12 wk (N=NR, NR) | . | 11.5 ± 0.7 vs 11.0 ± 0.7; NS
| EBF vs 1.5 g/dL protein and 55:45 whey:casein ratio FF | Hb (mean ± SD/SE, g/dl) @ time NR ≤12 wk (N=NR, NR) | . | 11.5 ± 0.7 vs 11.8 ± 1.1; NS
| EBF vs 1.3 g/dL protein and 55:45 whey:casein ratio FF | Hb (mean ± SD/SE, g/dl) @ time NR ≤12 wk (N=NR, NR) | . | 11.5 ± 0.7 vs 11.2 ± 1.1; NS
| EBF vs 1.4 g/dL protein and 60:40 whey:casein ratio FF | Hb (mean ± SD/SE, g/dl) @ time NR ≤12 wk (N=NR, NR) | . | 11.5 ± 0.7 vs 11.6 ± 0.7; NS
| EBF vs 1.4 g/dL protein and 20:80 whey:casein ratio FF | Hb (mean ± SD/SE, g/dl) @ time NR ≤12 wk (N=NR, NR) | . | 11.5 ± 0.7 vs 11.0 ± 0.7; NS
Wu 2011 ^23^; NRCT; China | FF vs EBF | Fe (mean ± SD, indicator NR) @ 4 wk (N=30, 30) | . | 112.93 ± 27.39 vs 111.23 ±26.18; NS
| | Fe (mean ± SD, indicator NR) @ 8 wk (N=30, 30) | . | 74.00 ± 24.3 vs 76.52 ± 24.6; NS

* Abbreviations: BF – breastfed/breastfeeding, CI – confidence interval, EBF – exclusively breastfed/exclusive breastfeeding, Fe – iron, FF – formula fed/formula feeding, Hb – hemoglobin, Hct – hematocrit, MCV – mean corpuscular volume, N – analytic sample size, NR – not reported, NRCT – non-randomized controlled trial, NS – nonsignificant, OR – odds ratio, PCS – prospective cohort study, RBC – red blood cell, RCS – retrospective cohort study, RDW – red cell distribution width, SD – standard deviation, SE – standard error, SF – serum ferritin

† Exposures, from the articles included in the body of evidence, which address ever vs never consuming human milk or vice versa

‡ Outcomes, from the articles included in the body of evidence, which address iron status including iron deficiency and anemia

§ In the study by Amano et al 2019 the reported hematocrit values may be inaccurate

Table 2 Risk of bias for non-randomized controlled trials examining the relationship between ever vs never consuming human milk and iron status^*^ ^†^

Study | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Bradley 1993 ^2^ | Serious | Serious | Moderate | Low | Serious | Low | Low
Lönnerdal 1990 ^12^ | Serious | No information | Moderate | Moderate | No information | Low | Serious
Wu 2011 ^23^ | Critical | Low | Moderate | Moderate | Low | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 3 Risk of bias for observational studies examining the relationship between ever vs never consuming human milk and iron status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Jochum 1995 ^9^ | Serious | Low | Serious | Low | Serious | Low | Low
Amano 2019 ^1^ | Serious | Serious | Serious | Low | Low | Low | Low
Cusick 2007 ^3^ | Serious | Critical for persistent anemia | Serious | Moderate | Serious | Moderate | Serious

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

#### Description of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 4)

Five articles present evidence comparing iron status in infants who consumed human milk for different durations.^2,7,8,16,20^

##### Population

The samples of infants were from the United States, Iceland, Israel, and Japan and a multinational sample was from Austria, Germany, Greece, Hungary, Italy, Portugal, Spain, Sweden, and the UK. Three studies followed participants starting at or close to their birth,^2,7,20^ 1 study enrolled participants by 30 days of age,^16^ and 1 followed participants starting at about 4 months.^8^ Participants in the U.S. study were mostly White,^2^ participants in the multinational study were all White,^16^ participants in the study from Iceland had Icelandic parents,^20^ and participants in the study from Israel were Arab and about 61% were from low-income families.^8^ Isomura et al^7^ did not report demographic information.

##### Interventions/exposures and comparators

Three studies examined the number of months infants consumed human milk as a continuous variable.^7,16,20^

Two studies grouped infants into categories by duration of human milk consumption. Jaber^8^ compared infants who consumed human milk for <3, 5-6, and >6 months (note: the article did not include a duration of 3-5 months). Bradley et al^2^ compared infants who consumed human milk ≥6 months with infants who initially consumed human milk (range 1-8 weeks) and then, after mothers decided to stop feeding human milk, were randomized into 2 groups fed infant formulas with different levels of iron.

In addition to human milk, some infants consumed infant formula, complementary foods and beverages, and/or iron supplements prior to the measurement of iron status.

- Bradley et al^2^ specified that infants could consume up to 1 supplemental feeding per day of a low-iron formula. Isomura et al^7^ estimated that, at 1 month, half of infants were partially breastfed and 8% of infants consumed <5% of their total milk as human milk, and by the time of the 6-month outcome measure, half of infants were partially breastfed and 35% of infants consumed <5% of their total milk as human milk. Male et al^16^ reported that, by the 12-month outcome measure, infants had been partially breastfed for an average of 3.6 months (range 0-12 months) and that iron content of formulas ranged from 5-14 mg/L. In the study by Thorsdottir et al,^20^ about 10% and 25% of infants were fed some formula by 1 and 6 months of age, respectively. Jaber^8^ did not report data about infant formula consumption.
- Infants in the analyses reported by Bradley et al^2^ could consume complementary foods and beverages, including iron-fortified cereals, starting at 4 months (i.e., prior to the outcome measures at 6 and 12 months). Isomura et al^7^ noted that all infants consumed complementary foods by 6 months, when outcomes were measured. Jaber^8^ reported that at 12 months, when outcomes were measured, about 68% of infants were consuming a varied diet. In addition, 1 infant had consumed tea for a short time during the first month of life, and 2 infants had consumed cow milk for short periods (not quantified). Male et al^16^ stated that all infants were fed complementary foods by the outcome measure, at 12 months, all commercially prepared cereals were iron fortified, and in the 3-month period preceding the outcome measures 91% of infants consumed meat almost every day. Participants also consumed complementary beverages; cow milk was introduced at an average age of 10 months (range 1-12 months) and, at 12 months, about half of infants consumed follow-on formula. Thorsdottir et al^20^ noted that the national recommendation at the time of the study was to wean to cow milk starting at 6 months of age. Accordingly, 40% of 6-month-olds consumed cow milk, and by the time of the outcome measure at 12 months, 98% of infants consumed cow milk. Intake of complementary foods was not quantified.
- Bradley et al^2^ reported that mineral supplements were not prescribed to any infants, and Isomura et al^7^ noted that Japan did not have a policy recommendation for infants to take iron supplements at the time of the study. On the other hand, Male et al^16^ reported that 11% of infants took iron supplements in the 3-month period before the outcome measure (i.e., 9-12 months) and Jaber^8^ reported that the proportion of infants taking iron supplements rose from 12-13% under age 6 months to nearly 75% over age 6 months. Thorsdottir et al^20^ did not quantify infant intake of iron supplements.

##### Outcomes

Three studies examined iron deficiency or anemia. Jaber^8^ defined anemia at 12 months as hemoglobin <11 g/dL. Thorsdottir et al^20^ defined iron deficiency at 12 months as serum ferritin <12 μg/l and mean corpuscular volume <74 fl. Male et al^16^ defined iron deficiency at 12 months as the presence of ≥2 of the following abnormal iron status indicators: low mean corpuscular volume (<70 fl), low serum ferritin (<10 μg/L), low transferrin saturation (<10%), high transferrin receptor (>4.4 mg/L). Iron deficiency anemia at 12 months was defined as anemia (hemoglobin <11.0 g/dL) plus ≥2 of the abnormal iron status indicators listed above.

Four studies^2,7,16,20^ examined iron indicators, including hemoglobin, hematocrit, mean corpuscular volume, serum ferritin, serum iron, transferrin receptor, and transferrin saturation measured at ages 6 and/or 12 months.

#### Synthesis and assessment^v^ of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 4)

The evidence examining the association between the duration of any human milk consumption among infants fed human milk and iron status is inconclusive. In the synthesis and assessment of the evidence that follows, several limitations are described that make it difficult to draw a conclusion.

Consistency: The evidence has limited consistency.

- [underlined: Iron deficiency and anemia]: The evidence available from 3 studies did not show a consistent association between the duration of any human milk consumption and iron deficiency or anemia.
  ○ Jaber^8^ and Thorsdottir et al^20^ both reported statistically significant associations between longer durations of human milk consumption and favorable outcomes. Jaber^8^ found that significantly more infants who consumed human milk for <3 months or for 5-6 months had anemia at 12 months than infants who consumed human milk for >6 months (note: the article did not include a duration of 3-5 months). Thorsdottir et al,^20^ likewise, found that the duration of human milk feeding was significantly shorter among 12-month-old infants with iron deficiency (i.e., serum ferritin <12 μg/l and mean corpuscular volume <74 fL) than among those without.
  ○ Male et al^16^ reported no significant associations between the duration of full or partial breastfeeding between 0-12 months and iron deficiency, anemia, or iron deficiency anemia at 12 months. The analyses were likely to have sufficient statistical power because they examined duration as a continuous variable among the entire sample of 488 infants.
  ○ This inconsistency may be due to some important differences between the studies.
    ■ Participants in the study by Male et al^16^ were all White, but were from several different European countries. Participants in the study by Thorsdottir et al^20^ all had Icelandic parents. Participants in the study by Jaber^8^ were all Arab and predominantly (61%) from low-income families.
    ■ The samples may have differed in their human milk consumption, although differences in reporting make it difficult to compare across studies. Participants in the study by Male et al^16^ were partially breastfed for a mean of 3.6 ± 3.9 months. Thorsdottir et al^20^ reported that 77% of infants were breastfed at 6 months and about 12% were breastfed at 12 months. In the analysis by Jaber^8^, most infants consumed human milk for >6 months (N=168, compared with N=29 and N=87 for durations of <3 and 5-6 months, respectively).
    ■ The sample studied by Thorsdottir et al^20^ may have consumed more cow milk and less infant formula than the sample studied by Male et al.^16^ Thorsdottir et al^20^ reported that about 25% and 0% of infants consumed infant formula at 6 and 12 months, respectively, but that 40% and 98% of infants consumed cow’s milk. Male et al^16^ reported that formula (with a range of 5-14 mg/L iron) was consumed for a mean of 7.9 ± 3.9 months and that cow milk was introduced at a mean of 10.0 ± 2.6 months. Jaber^8^ did not report formula consumption but did report that only 2 infants consumed cow milk (for short periods).
    ■ Fewer infants in the study by Male et al^16^ were given iron supplements than in the study by Jaber^8^ (11% and nearly 75%, respectively). It is harder to determine whether the samples differed in complementary feeding practices. Male et al^16^ reported that 91% of infants consumed meat almost daily and Jaber^8^ reported that about 68% of infants were consuming a varied diet by the time of the outcome measure. Thorsdottir et al^20^ did not report similar information.
    ■ Male et al^16^ accounted for more of the key confounders listed on the analytic framework than Jaber^8^ and Thorsdottir et al.^20^ Jaber^8^ did not adjust for any confounders, Thorsdottir et al^20^ and Male et al^16^ both adjusted for sex and types and amounts of complementary foods and beverages, and Male et al^16^ additionally adjusted for socioeconomic status, vitamin/mineral supplements, and birthweight. None of the studies adjusted for race/ethnicity, but each included a homogeneous sample.
- [underlined: Other iron status outcomes]: The evidence available from 4 studies did not show a consistent association between the duration of any human milk consumption and other iron status outcomes.
  ○ Thorsdottir et al^20^ reported significant correlations between the total duration of human milk consumption and serum ferritin and the ratio of transferrin receptor to serum ferritin at 12 months; longer duration was associated with better iron status. However, this study may be prone to reporting bias because it is unclear whether other outcome measures described in the study (i.e., mean corpuscular volume, hemoglobin, and transferrin receptor) were not assessed at 12 months or were not reported (possibly because they lacked statistical significance).
  ○ The remaining 3 studies did not find any significant associations between duration variables and hemoglobin, hematocrit, serum ferritin, or serum iron at 6 and 12 months and mean corpuscular volume, transferrin saturation, or transferrin receptor at 12 months.^2,7,16^ The analyses in the study by Bradley et al^2^ may have lacked statistical power because they compared small groups of infants fed human milk for different durations. Isomura et al^7^ and Male et al,^16^ however, used their full samples (N=86 and N=488, respectively) to examine duration as a continuous variable.
  ○ The inconsistencies in the findings may be due to differences between samples in the consumption of human milk, infant formula, cow milk, complementary foods, and iron supplements.
    ■ Bradley et al^2^ studied infants fed human milk for 1-8 weeks and infants fed human milk for ≥6 months. Isomura et al^7^ estimated that, at 6 months, 82% of infants were partially to completely breastfed (i.e., considering the proportion of infants’ total milk intake that was human milk). As described previously, Thorsdottir et al^20^ reported that 77% of infants were breastfed at 6 months and about 12% were breastfed at 12 months, and participants in the study by Male et al^16^ were breastfed for a mean of 3.6 ± 3.9 months.
    ■ As described previously, the sample in the study by Male et al^16^ may have consumed more infant formula and less cow milk than the sample in the study by Thorsdottir et al.^20^ Bradley et al^2^ specified that breastfed infants could consume up to 1 supplemental feeding per day of a low-iron formula and then consumed a low-iron formula from the end of the breastfeeding period (i.e., 1-8 weeks or ≥ 6 months, depending on the group) until age 12 months. Isomura et al^7^ specified that, at 6 months, 35% of infants were predominantly formula-fed (i.e., <5% of their total milk intake was human milk). Neither Bradley et al^2^ nor Isomura et al^7^ reported cow milk intake.
    ■ Thorsdottir et al^20^ did not report intake of complementary foods, but the other studies specified that infants were consuming complementary foods and beverages by the time outcomes were measured. Male et al^16^ reported that 91% of infants consumed meat almost every day by the time outcomes were measured.
    ■ Thorsdottir et al^20^ and Isomura et al^7^ did not report supplement use, although Isomura et al^7^ noted that infant supplementation was not recommended in Japan at the time of the study. Bradley et al^2^ reported that mineral supplements were not prescribed to any infants and Male et al^16^ reported that 11% of infants were given iron supplements at the time of the outcome measure.

Precision: The precision of the evidence cannot be adequately assessed.

- The body of evidence had only 5 studies, and most were likely to have sufficient statistical power (i.e., 2 studies reported significant findings,^8,20^ and 2 with nonsignificant findings examined duration as a continuous variable using the entire sample^7,16^). However, an assessment of precision is hindered by the lack of reporting of data that would allow for a comparison of the magnitude of effect across studies. The studies that reported significant findings did not report effect sizes,^8,20^ and one of the studies that reported a nonsignificant association did not report any data.^16^

Directness: The evidence has moderate directness.

- Three of the 5 articles reported study objectives that included the examination of whether the duration of human milk consumption is related to iron status.^7,16,20^

Generalizability: The evidence has limited generalizability.

- Iron deficiency, anemia, and iron deficiency anemia were examined at 12 months and not at any other time during the birth to 24 month period. None of the studies examining iron deficiency and anemia were conducted in the United States, but rather represent White European,^16^ Icelandic,^20^ and low-income Arab^8^ populations. A large proportion of the sample examined by Thorsdottir et al^20^ consumed cow milk and a large proportion of the sample examined by Jaber^8^ took iron supplements prior to 12 months, which may limit the generalizability of the findings to the United States.
- With regard to other iron status outcomes, the studies measured outcomes at 6 and 12 months, only, and not the rest of the birth to 24 month period. Only 1 study was from the United States, and participants in that study were mostly White.^2^ The remaining studies included White European children,^16^ Icelandic children,^20^ and children from Japan.^7^ As described above, findings from the Icelandic sample, where cow milk was consumed by a large proportion of infants before 12 months, may not be generalizable to the United States.

Risk of bias: There is a limited likelihood that the design and conduct of the studies have prevented or minimized bias.

- None of the studies accounted for all of the key confounders listed on the analytic framework although, as noted above, Male et al^16^ accounted for most of them. In addition, none of the studies accounted for any of the other factors to be considered from the analytic framework, although Male et al^16^ did adjust for infectious illness, which is related to inflammatory biomarkers. The lack of adjustment for the timing of cord clamping is worth noting due to its potential to impact anemia.^vi^
- The studies were prone to other risks of bias, which varied between studies (Tables 5 and 6).

Table 4 Evidence examining the relationship between the duration of any human milk consumption among infants fed human milk and iron status^*^

Article; Study design; Country | Duration of any human milk consumption exposure^†^ | Iron status outcome^‡^ | Significant associations | Nonsignificant associations
Bradley 1993 ^2^; NRCT; U.S. | BF 1-8 wk then High-Fe FF vs BF ≥6 mo | Hb (mean ± SD, g/dL) @ 6 mo (N=26, 37) | . | 11.3 ± 0.7 vs 11.8 ± 1.4; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=21, 37) | . | 11.7 ± 1.1 vs 12.1 ± 1.0; NS
| | Hct (mean ± SD, %) @ 6 mo (N=25, 36) | . | 33 ± 2 vs 35 ± 3; NS
| | Hct (mean ± SD, %) @ 12 mo (N=20, 37) | . | 34 ± 2 vs 36 ± 2; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=26, 31) | . | 40 ± 18 vs 45 ± 43; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=21, 30) | . | 31 ± 23 vs 23 ± 28; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=24, 16) | . | 108 ± 51 vs 119 ± 75; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=19, 16) | . | 106 ± 58 vs 168 ± 105; NS
| BF 1-8 wk then Low-Fe FF vs BF ≥6 mo | Hb (mean ± SD, g/dL) @ 6 mo (N=21, 37) | . | 11.5 ± 0.8 vs 11.8 ± 1.4; NS
| | Hb (mean ± SD, g/dL) @ 12 mo (N=20, 37) | . | 11.9 ± 1.0 vs 12.1 ± 1.0; NS
| | Hct (mean ± SD, %) @ 6 mo (N=21, 36) | . | 34 ± 3 vs 35 ± 3; NS
| | Hct (mean ± SD, %) @ 12 mo (N=20, 37) | . | 35 ± 3 vs 36 ± 2; NS
| | SF (mean ± SD, μg/L) @ 6 mo (N=22, 31) | . | 29 ± 28 vs 45 ± 43; NS
| | SF (mean ± SD, μg/L) @ 12 mo (N=19, 30) | . | 24 ± 22 vs 23 ± 28; NS
| | Serum Fe (mean ± SD, μg/dL) @ 6 mo (N=19, 16) | . | 113 ± 52 vs 119 ± 75; NS
| | Serum Fe (mean ± SD, μg/dL) @ 12 mo (N=19, 16) | . | 109 ± 35 vs 168 ± 105; NS
Isomura 2011 ^7^; PCS; Japan | BF duration (mo) | Hb (β (95% CI), g/dL) @ 6 mo (N=86) | . | −0.24 (−0.69, 0.20); p=0.09
| | Hct (β (95% CI), %) @ 6 mo (N=86) | . | −0.33 (−0.74, 0.08); p=0.11
Jaber 2014 ^8^; PCS; Israel | Period of BF <3 vs 5-6 vs >6 mo | Anemic (%) @ 12 mo (N=29, 87, 168) | 44.8% vs 46.0% vs 25.6%; p=0.002 for >6 mo | .
Male 2001 ^16^; PCS; Multinational^§^ (Euro-Growth) | Duration of full or partial BF between 0-12 mo (mo) | Anemia (OR ± 95% CI) @ 12 mo (N=488) | . | Data NR; NS
| | ID (OR ± 95% CI) @ 12 mo (N=488) | . | Data NR; NS
| | IDA (OR ± 95% CI) @ 12 mo (N=488) | . | Data NR; NS
| | Hb (mean ± SD, g/L) @ 12 mo (N=488) | . | Data NR; NS
| | MCV (mean ± SD, fL) @ 12 mo (N=488) | . | Data NR; NS
| | logSF (mean ± SD, μg/L) @ 12 mo (N=488) | . | Data NR; NS
| | √TSAT (mean ± SD, %) @ 12 mo (N=488) | . | Data NR; NS
| | logTfR (mean ± SD, mg/L) @ 12 mo (N=488) | . | Data NR; NS
Thorsdottir 2003 ^20^; PCS; Iceland | Total BF duration (mo) | ID vs Non-ID @12 mo (N=19, 89) | Mean duration ± SD: 5.3 ± 2.2 vs 7.9 ± 3.2; p=0.001 | .
| | Log SF (adjusted r2) @12 mo (N=105) | 0.14; p=0.027 | .
| | TfR:log SF (adjusted r2) @12 mo (N=94) | 0.07; p=0.005 | .

* Abbreviations: BF – breastfed/breastfeeding, CI – confidence interval, Fe – iron, FF – formula fed/formula feeding, Hb – hemoglobin, Hct – hematocrit, ID – iron deficiency, IDA – iron deficiency anemia, MCV – mean corpuscular volume, N – analytic sample size, NR – not reported, NRCT – non-randomized controlled trial, NS – nonsignificant, OR – odds ratio, PCS – prospective cohort study, RBC – red blood cell, SD – standard deviation, SF – serum ferritin, TfR – transferrin receptor, TSAT – transferrin saturation

† Exposures, from the articles included in the body of evidence, which address the duration of any human milk consumption among infants fed human milk

‡ Outcomes, from the articles included in the body of evidence, which address iron status including iron deficiency and anemia

§ Austria, Germany, Greece, Hungary, Italy, Portugal, Spain, Sweden, UK

Table 5 Risk of bias for the non-randomized controlled trial examining the relationship between the duration of any human milk consumption among infants fed human milk and iron status^*^ ^†^

Study | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Bradley 1993 ^2^ | Serious | Serious | Moderate | Low | Serious | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 6 Risk of bias for observational studies examining the relationship between the duration of any human milk consumption among infants fed human milk and iron status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Isomura 2011 ^7^ | Serious | Low | Serious | Moderate | Moderate | Low | Serious
Jaber 2014 ^8^ | Serious | Low | Serious | Low | Low | Low | Low
Male 2001 ^16^ | Serious | Moderate | Serious | Low | Low | Moderate | Low
Thorsdottir 2003 ^20^ | Serious | Low | Serious | Low | Low | Low | Serious

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Zinc status

Five articles, published between 1986 and 1994, examined the relationships of ever compared with never consuming human milk, and different durations of any human milk consumption, with zinc status from birth to 24 months.^2,11,12,17,18^

No evidence was identified that met the inclusion criteria to examine different durations of exclusive human milk consumption before the introduction of infant formula or different intensities, proportions, or amounts of human milk consumed by mixed-fed infants.

#### Description of the evidence comparing ever with never consuming human milk (Table 7)

Four articles presented evidence comparing the zinc status of infants who ever consumed human milk with that of infants who never consumed human milk.^2,11,12,18^

##### Population

The samples of infants were from the United States, China, Germany, and the UK. The investigators followed participants starting at birth. Most studies included infants born full-term and/or with a normal birthweight; however, Salim et al^18^ included participants born with a gestational age of 32 to 42 weeks and 28% of participants had low birth weight. Participants from the U.S.-based study were mostly White.^2^ Authors of the remaining 3 studies did not report the racial or ethnic composition of their samples.

##### Interventions/exposures and comparators

Infants who consumed human milk:

- Two studies included a group of infants fed human milk exclusively. In the study by Lombeck and Fuchs,^11^ infants were only fed human milk throughout the observation period. Lönnerdal and Chen^12^ did not specify the duration of the exclusive human milk-feeding period.
- One study, by Bradley et al,^2^ included groups of infants fed human milk, but not exclusively. One group was fed human milk ≥6 months with up to 1 supplemental feeding per day of a low-iron formula. The other 2 groups consumed human milk for 1 to 8 weeks and were then randomized to consume formulas with different levels of iron.
- One study, by Salim et al,^18^ did not report sufficient information to determine the exclusivity of the human milk exposure.

Infants who never consumed human milk:

- In the study by Lombeck and Fuchs,^11^ parents who decided to formula feed selected the formula. Families with no history of atopic disease chose 1 of 11 different cow milk formulas, whereas study staff recommended partially hydrolyzed whey protein formula to parents of children with a family history of atopy.
- In 3 studies, parents who decided to formula feed were assigned to a formula by research staff. Bradley et al,^2^ Lönnerdal and Chen,^12^ and Salim et al^18^ randomly allocated infants to formulas with different levels of iron, different levels and sources of protein, and different levels of copper, respectively.

In addition to human milk and infant formula, some infants consumed complementary foods and beverages and/or supplements prior to the measurement of zinc status.

- In the study by Bradley et al,^2^ infants could consume complementary foods and beverages, including iron-fortified cereals, starting at 4 months (i.e., prior to the outcome measures at 6 and 12 months). Mineral supplements were not prescribed to any of the infants.
- Lönnerdal and Chen^12^ and Salim et al^18^ did not report whether any infants received complementary foods and beverages or supplements prior to the measurement of outcomes between 2 and 12 weeks.

##### Outcomes

The studies measured serum zinc at 2, 4, 8, and 12 weeks^12^ and at 6 and 12 months,^2^ plasma zinc at 8 to 10 weeks^18^ and 4 months,^11^ and urinary zinc at 4 months.^11^

#### Synthesis and assessment^vii^ of the evidence comparing ever with never consuming human milk (Table 7)

The evidence examining the association between ever, compared with never, consuming human milk and zinc status from birth to 24 months is inconclusive. In the synthesis and assessment of the evidence that follows, several limitations are described that make it difficult to draw a conclusion.

Consistency: The evidence has limited consistency.

- The evidence is inconsistent with regard to the statistical significance of the findings, and there is not enough information to determine whether this relates to statistical power.
  ○ Two of 4 studies reported statistically significant associations between ever, compared with never, consuming human milk and zinc status.^11,18^ All 4 studies also reported nonsignificant associations.
  ○ This inconsistency may be due to differences in statistical power, but it is difficult to know for sure because none of the studies reported power calculations.
  ○ This inconsistency may also be due to methodological differences, such as differences in the exposure (which included different durations of any and exclusive human milk feeding), comparator (which included several different types of infant formula), outcome (which included serum, plasma, and urinary zinc measured at time points between 2 weeks and 12 months), or other factors (e.g., confounding).
- Both statistically significant associations showed that infants who ever consumed human milk had higher zinc status than infants who never consumed human milk.
  ○ Salim et al^18^ found that plasma zinc was significantly higher at 8 to 10 weeks in infants fed human milk than in infants fed a high-copper formula. However, plasma zinc was not significantly different between infants fed human milk and infants fed a low-copper formula.
  ○ Lombeck and Fuchs^11^ found that plasma zinc was significantly higher at 120 days in infants fed human milk exclusively than in infants fed cow’s milk formula. When the authors stratified this analysis by sex, they found that the difference was significant in female participants but not in male participants. Plasma zinc was not significantly different between infants fed human milk and infants fed hypoallergenic (i.e., cow’s milk whey hydrolysate) formula. Urinary zinc was not significantly different between infants fed human milk and infants fed either type of infant formula; however, the authors did not report the sample sizes or data so this finding is difficult to interpret.

Precision: The precision of the evidence cannot be adequately assessed.

- There is not enough information to determine whether the body of evidence has an adequate number of sufficiently powered studies.
  ○ There are only 4 studies in the body of evidence.
  ○ As previously described, there is not enough information to determine whether the studies had sufficient statistical power to examine the relationships of interest.
- Across the 2 statistically significant associations, mean plasma zinc levels differed in infants with similar exposures; for example, infants fed human milk had mean plasma zinc levels of 17.6 ± 5.8 μmol/l^18^ and 12.15 ± 1.73 μmol/l.^11^ The difference is difficult to interpret because of methodological differences between studies, such as differences in diet (e.g., Salim et al^18^ did not report whether human milk-fed infants consumed formula or complementary foods and beverages) and differences in the age at outcome measure (i.e., 8 to 10 weeks and 120 days).

Directness: The evidence has moderate directness.

- Three of the 4 articles reported study objectives that included the comparison of zinc status between human milk-fed and formula-fed infants.

Generalizability: The evidence has limited generalizability.

- Participants in the U.S. study were primarily White and no other studies reported race or ethnicity.
- Salim et al^18^ examined a sample in which 28% of infants were born with low birth weight.
- Participants’ exposure years were from the early 1980s to 1991. Therefore, the findings may not be generalizable to infants who consume formulas currently on the market.

Risk of bias: There a limited likelihood that the design and conduct of the studies have prevented or minimized bias.

- Two studies accounted for none of the key confounders on the analytic framework,^12,18^ and the remaining 2 studies only accounted for 1 key confounder.^2,11^
- The studies were prone to other risks of bias (Tables 8 and 9), which varied between studies.

Table 7 Evidence examining the relationship between ever vs never consuming human milk and zinc status^*^

Article; Study design; Country | Ever vs never consuming human milk exposure^†^ | Zinc status outcome^‡^ | Significant associations | Nonsignificant associations
Bradley 1993 ^2^; NRCT; U.S. | High-Fe FF vs BF ≥6 mo | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=31, 17) | . | 77.0 ± 17.8 vs 72.6 ± 8.9; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=20, 20) | . | 76.1 ± 13.3 vs 74.8 ± 14.5; NS
| High-Fe FF vs BF 1-8 wk then High-Fe FF | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=31, 23) | . | 77.0 ± 17.8 vs 75.0 ± 14.7; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=20, 18) | . | 76.1 ± 13.3 vs 71.4 ± 13.1; NS
| High-Fe FF vs BF 1-8 wk then Low-Fe FF | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=31, 18) | . | 77.0 ± 17.8 vs 76.9 ± 19.3; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=20, 16) | . | 76.1 ± 13.3 vs 72.1 ± 16.7; NS
| Low-Fe FF vs BF ≥6 mo | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=27, 17) | . | 76.4 ± 13.5 vs 72.6 ± 8.9; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=17, 20) | . | 78.2 ± 17.3 vs 74.8 ± 14.5; NS
| Low-Fe FF vs BF 1-8 wk then High-Fe FF | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=27, 23) | . | 76.4 ± 13.5 vs 75.0 ± 14.7; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=17, 18) | . | 78.2 ± 17.3 vs 71.4 ± 13.1; NS
| Low-Fe FF vs BF 1-8 wk then Low-Fe FF | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=27, 18) | . | 76.4 ± 13.5 vs 76.9 ± 19.3; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=17, 16) | . | 78.2 ± 17.3 vs 72.1 ± 16.7; NS
Lombeck 1994 ^11^; PCS; Germany | EBF vs cow’s milk FF | Plasma Zn (mean ± SD, μmol/l) @ 120 ± 15 d (N=49, 44) | 12.15 ± 1.73 vs 11.09 + 1.71; p=0.004 | .
| | In female subsample (N=21,24) | 12.38 ± 1.88 vs 10.57 ± 1.42; p=0.0007 | .
| | In male subsample (N=28, 20) | . | 11.98 ± 1.64 vs 11.70 ± 1.87; NS
| | Urinary Zn (units NR) @ 120 ± 15 d (N=8-12 per group, NR) | . | NS, data NR
| EBF vs hypoallergenic FF | Plasma Zn (mean ± SD, μmol/l) @ 120 ± 15 d (N=49, 35) | . | 12.15 ± 1.73 vs 12.35 ± 1.65; NS
| | In female subsample (N=21,14) | . | 12.38 ± 1.88 vs 12.93 ± 1.44; NS
| | In male subsample (N=28, 21) | . | 11.98 ± 1.64 vs 11.95 ± 1.68; NS
| | Urinary Zn (units NR) @ 120 ± 15 d (N=8-12 per group, NR) | . | NS, data NR
Lönnerdal 1990 ^12^; NRCT; China | EBF vs 1.4 g/dL protein and 55:45 whey:casein ratio FF | Serum Zn (mean μg/ml) @ 2 wk (N=NR, NR) | . | ~0.5 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 4 wk (N=NR, NR) | . | ~0.55 vs ~0.55; NS
| | Serum Zn (mean μg/ml) @ 8 wk (N=NR, NR) | . | ~0.6 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 12 wk (N=NR, NR) | . | ~0.75 vs ~0.7; NS
| EBF vs 1.5 g/dL protein and 55:45 whey:casein ratio FF | Serum Zn (mean μg/ml) @ 2 wk (N=NR, NR) | . | ~0.5 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 4 wk (N=NR, NR) | . | ~0.55 vs ~0.55; NS
| | Serum Zn (mean μg/ml) @ 8 wk (N=NR, NR) | . | ~0.6 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 12 wk (N=NR, NR) | . | ~0.75 vs ~0.8; NS
| EBF vs 1.3 g/dL protein and 55:45 whey:casein ratio FF | Serum Zn (mean μg/ml) @ 2 wk (N=NR, NR) | . | ~0.5 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 4 wk (N=NR, NR) | . | ~0.55 vs ~0.55; NS
| | Serum Zn (mean μg/ml) @ 8 wk (N=NR, NR) | . | ~0.6 vs ~0.7; NS
| | Serum Zn (mean μg/ml) @ 12 wk (N=NR, NR) | . | ~0.75 vs ~0.65; NS
| EBF vs 1.4 g/dL protein and 60:40 whey:casein ratio FF | Serum Zn (mean μg/ml) @ 2 wk (N=NR, NR) | . | ~0.5 vs ~0.5; NS
| | Serum Zn (mean μg/ml) @ 4 wk (N=NR, NR) | . | ~0.55 vs ~0.55; NS
| | Serum Zn (mean μg/ml) @ 8 wk (N=NR, NR) | . | ~0.6 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 12 wk (N=NR, NR) | . | ~0.7 vs ~0.65; NS
| EBF vs 1.4 g/dL protein and 20:80 whey:casein ratio FF | Serum Zn (mean μg/ml) @ 2 wk (N=NR, NR) | . | ~0.5 vs ~0.55; NS
| | Serum Zn (mean μg/ml) @ 4 wk (N=NR, NR) | . | ~0.55 vs ~0.55; NS
| | Serum Zn (mean μg/ml) @ 8 wk (N=NR, NR) | . | ~0.6 vs ~0.6; NS
| | Serum Zn (mean μg/ml) @ 12 wk (N=NR, NR) | . | ~0.75 vs ~0.65; NS
Salim 1986 ^18^; NRCT; UK | BF vs Low-Cu FF | Plasma Zn (mean ± SD μmol/l) @ 8-10 wk (N=30, 38) | . | 17.6 ± 5.8 vs 15.8 ± 4.7; NS
| BF vs High-Cu FF | Plasma Zn (mean ± SD μmol/l) @ 8-10 wk (N=30, 30) | 17.6 ± 5.8 vs 13.8 ± 4.3; p<0.005 | .

* Abbreviations: BF – breastfed/breastfeeding, CI – confidence interval, Cu – copper, EBF – exclusively breastfed/exclusive breastfeeding, Fe – iron, FF – formula fed/formula feeding, N – analytic sample size, NR – not reported, NRCT – non-randomized controlled trial, NS – nonsignificant, PCS – prospective cohort study, SD – standard deviation, SE – standard error, Zn – zinc

† Exposures, from the articles included in the body of evidence, which address ever vs never consuming human milk or vice versa

‡ Outcomes, from the articles included in the body of evidence, which address zinc status

Table 8 Risk of bias for non-randomized controlled trials examining the relationship between ever vs never consuming human milk and zinc status^*^ ^†^

Study | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Bradley 1993 ^2^ | Serious | Serious | Moderate | Low | Serious | Low | Low
Lönnerdal 1990 ^12^ | Serious | No information | Moderate | Moderate | No information | Low | Serious
Salim 1986 ^18^ | Serious | Low | Serious | Low | Serious | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 9 Risk of bias for the observational study examining the relationship between ever vs never consuming human milk and zinc status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Lombeck 1994 ^11^ | Serious | Low | Serious | Low | Low | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

#### Description of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 10)

Two articles presented evidence comparing zinc status in infants who consumed human milk for different durations.^2,17^

##### Population

The study samples were full-term infants from the United States and Denmark who were followed from birth. Participants in the U.S.-based study were mostly White^2^, and the study from Denmark did not report race or ethnicity.^17^

##### Interventions/exposures and comparators

Michaelsen et al^17^ examined the duration (but did not report the unit of time) that infants were fed human milk at least once per day. The intake of infant formula, complementary foods and beverages, and supplements were not reported.

Bradley et al^2^ compared infants who consumed human milk for ≥6 months with infants who initially consumed human milk (range 1-8 weeks) and then, after mothers decided to stop feeding human milk, were randomized into 2 groups fed infant formulas with different levels of iron. Human milk-fed infants could consume up to 1 supplemental feeding per day of a low-iron formula. Infants could consume complementary foods and beverages starting at 4 months (i.e., prior to the outcome measures at 6 and 12 months). Mineral supplements were not prescribed to any of the infants.

##### Outcomes

The studies measured serum zinc at 6, 9, and 12 months.

#### Synthesis and assessment^viii^ of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 10)

The evidence examining the association between the duration of any human milk consumption and zinc status from birth to 24 months is inconclusive. In the synthesis and assessment of the evidence that follows, several limitations are described that make it difficult to draw a conclusion.

Consistency and Precision: The consistency and precision of the evidence cannot be adequately assessed.

- With only 2 articles in the body of evidence, there are insufficient data to comment on consistency or precision. Further, Michaelsen et al^17^ did not report data. Neither article reported statistical power.

Directness: The evidence has limited directness.

- Neither article reported study objectives that included the analysis of zinc status based on the duration of human milk consumption.

Generalizability: The evidence has limited generalizability.

- With only 2 studies, there was not a large number of participants overall. Further, participants in the study were primarily White and the study from Denmark did not report race or ethnicity.

Risk of bias: There is a limited likelihood that the design and conduct of the studies have prevented or minimized bias.

- One of the studies accounted for none of the key confounders on the analytic framework,^17^ and the second study only accounted for 1 key confounder.^2^
- The studies were prone to other risks of bias (Tables 11 and 12) which varied between studies.

Table 10 Evidence examining the relationship between the duration of any human milk consumption among infants fed human milk and zinc status^*^

Article; Study design; Country | Duration of any human milk consumption exposure^†^ | Zinc status outcome^‡^ | Significant associations | Nonsignificant associations
Bradley 1993 ^2^; NRCT; U.S. | BF 1-8 wk then High-Fe FF vs BF ≥6 mo | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=23, 17) | . | 75.0 ± 14.7 vs 72.6 ± 8.9; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=18, 20) | . | 71.4 ± 13.1 vs 74.8 ± 14.5; NS
| BF 1-8 wk then Low-Fe FF vs BF ≥6 mo | Serum Zn (mean ± SD, μg/dL) @ 6 mo (N=18, 17) | . | 76.9 ± 19.3 vs 72.6 ± 8.9; NS
| | Serum Zn (mean ± SD, μg/dL) @ 12 mo (N=16, 20) | . | 72.1 ± 16.7 vs 74.8 ± 14.5; NS
Michaelsen 1994 ^17^; PCS; Denmark | Total duration of BF (unit of time NR) | Serum Zn (μmol/dL) @ 9 mo (N=57) | . | NS, data NR

* Abbreviations: BF – breastfed/breastfeeding, Fe – iron, FF – formula fed/formula feeding, N – analytic sample size, NR – not reported, NRCT – non-randomized controlled trial, NS – nonsignificant, PCS – prospective cohort study, SD – standard deviation, Zn – zinc

† Exposures, from the articles included in the body of evidence, which address the duration of any human milk consumption among infants fed human milk

‡ Outcomes, from the articles included in the body of evidence, which address zinc status

Table 11 Risk of bias for the non-randomized controlled trial examining the relationship between the duration of any human milk consumption among infants fed human milk and zinc status^*^ ^†^

Study | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Bradley 1993 ^2^ | Serious | Serious | Moderate | Low | Serious | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

Table 12 Risk of bias for the observational study examining the relationship between the duration of any human milk consumption among infants fed human milk and zinc status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Michaelsen 1994 ^17^ | Serious | Low | Serious | Moderate | Serious | Moderate | Serious

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Iodine status

No articles were identified that examined the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and iodine status from birth to 24 months.

### Vitamin B12 status

No articles were identified that examined the relationship between the duration, frequency, and volume of exclusive human milk and/or infant formula consumption and vitamin B12 status from birth to 24 months.

### Vitamin D status

One article, published in 2014, examined the relationship between the duration of any human milk consumption and vitamin D status from birth to 24 months.^19^

No evidence was identified that met the inclusion criteria to examine ever, compared with never, consuming human milk, different durations of exclusive human milk consumption before the introduction of infant formula, or different intensities, proportions, or amounts of human milk consumed by mixed-fed infants.

#### Description of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 13)

Thorisdottir et al^19^ observed a cohort of full term, singleton, Icelandic infants from birth to 12 months. They assessed the correlation between the number of months infants were fed human milk once or more per day and serum 25(OH)D at 12 months. The median duration of any human milk feeding was 8 months (interquartile range: 6, 10), and from 9 to 12 months it was estimated that about 22% of infants had regular intake of fortified products with vitamin D, 18% had regular intake of supplements with vitamin D, and 33% had regular intake of both fortified foods and supplements.

#### Synthesis and assessment^ix^ of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 13)

Insufficient evidence is available to examine the association between the duration of any human milk consumption and vitamin D status from birth to 24 months. The body of evidence consists of a single study, which found a nonsignificant correlation between the duration of any human milk feeding and vitamin D status at 12 months. The study accounted for 1 key confounder on the analytic framework and was prone to other risks of bias (Table 14).

Table 13 Evidence examining the relationship between the duration of any human milk consumption among infants fed human milk and vitamin D status^*^

Article; Study design; Country | Duration of any human milk consumption exposure^†^ | Vitamin D status outcome^‡^ | Significant associations | Nonsignificant associations
Thorsdottir 2014 ^19^; PCS; Iceland | Total BF duration (mo) | Serum 25(OH)D (correlation coefficient) @ 12 mo (N=76) | . | 0.08; p=0.502

* Abbreviations: BF – breastfed/breastfeeding, N – analytic sample size, PCS – prospective cohort study

† Exposures, from the articles included in the body of evidence, which address the duration of any human milk consumption among infants fed human milk

‡ Outcomes, from the articles included in the body of evidence, which address vitamin D status

Table 14 Risk of bias for the observational study that examines the relationship between the duration of any human milk consumption among infants fed human milk and vitamin D status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing outcome data | Outcome measurement | Selection of the reported result
Thorsdottir 2003 ^19^ | Serious | Moderate | Moderate | Low | Low | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Fatty acid status

Nine articles, published between 1986 and 2016, examined the relationships of ever compared with never consuming human milk, different durations of any human milk consumption, and different durations of exclusive human milk consumption before the introduction of infant formula with fatty acid status from birth to 24 months.^4–6,10,13–15,21,22^

No evidence was identified that met the inclusion criteria to examine different intensities, proportions, or amounts of human milk consumed by mixed-fed infants.

#### Description of the evidence comparing ever with never consuming human milk (Table 15)

Seven articles presented evidence comparing the fatty acid status of infants who ever consumed human milk with that of infants who never consumed human milk.^4–6,10,13–15^

##### Population

One study included a sample of infants from the United States and Canada.^6^ Four studies, from the same research group, included different participants who likely represented the same population of infants in Australia.^4,13–15^ One study included a sample of infants from Spain.^5^ The remaining study did not report the study location, which was likely either Germany or Belgium.^10^

All of the studies followed full-term infants with normal birthweights starting at or close to their birth. Gil et al^5^ included participants with vaginal deliveries, only. The participants in 2 of the 4 studies from Australia were White, only,^14,15^ and the remaining studies did not report the racial or ethnic composition of their samples.

##### Interventions/exposures and comparators

Infants who consumed human milk:

- Two studies included a group of infants fed human milk exclusively for the duration of the study^5,6^; however, Gil et al^5^ specified that infants’ initial 3 feedings in the hospital after delivery were a 5% dextrose solution.
- The 4 studies from Australia examined infants fed human milk, but not exclusively.
  ○ In the earliest study, infants were fed human milk, but not infant formula, for the first 16 weeks (complementary feeding was not reported), and ≤ 120 ml of infant formula could be supplemented per day between 16 weeks and the final outcome measure at 30 weeks.^13^
  ○ In the studies from 1999 and 2000, human milk feeding could be supplemented with infant formula in the amount of ≤ 200 ml per week.^14,15^ The study from 1999 did not report complementary feeding, but the study from 2000 reported that about 36% of human milk-fed infants consumed complementary foods by the 16-week outcome measure.
  ○ Gibson et al^4^ recruited a group of infants whose mothers intended to feed human milk for the entire birth to 7-month observation period. At 7 months, 59% of infants in this group were consuming ≥ 80% of milk feeds as human milk, and 100% were consuming complementary foods and beverages.
- The remaining study did not report whether infants consumed complementary foods and beverages during the birth to 3-month observation period, so the exclusivity of the human milk exposure cannot be determined.^10^

Infants who never consumed human milk:

- In all of the studies, parents who decided to formula feed were randomly assigned to a formula by research staff. Each study included a standard infant formula as well as formulas supplemented with dietary nucleotides,^4,5^ linoleic acid (LA) and alpha-linolenic acid (ALA),^6,14^ docosahexaenoic acid (DHA),^13^ or arachidonic acid (AA) and DHA.^10,15^

##### Outcomes

The studies examined fatty acids from plasma and/or erythrocytes across a range of ages from 1 week to 7 months.

#### Synthesis and assessment^x^ of the evidence comparing ever with never consuming human milk (Table 15)

The strength of the evidence examining the association between ever, compared with never, consuming human milk and fatty acid status from birth to 24 months is moderate. In the synthesis and assessment of the evidence that follows, the strengths and limitations of the evidence are discussed.

Consistency: The evidence has moderate consistency.

- The evidence is consistent in showing that ever, compared with never, consuming human milk is related to fatty acid status, but the direction and strength of associations can vary depending on the composition of the infant formula fed to participants who never consumed human milk, as well as the specific types of fatty acids examined in the blood. For example, 3 studies compared infants fed human milk with infants fed a conventional infant formula and infants fed DHA- or DHA- and AA-supplemented formula.^10,13,15^ In comparison to consuming human milk, consuming a conventional infant formula was generally associated with significantly lower DHA levels, whereas consuming DHA- or DHA- and AA-supplemented formula was generally not associated with, or associated with significantly higher, DHA levels.
- It is likely that the composition of human milk similarly affects the significance and direction of the associations between ever, compared with never, consuming human milk and fatty acid status. However, the studies in this body of evidence were not designed to examine human milk composition or its effect on infant fatty acid status (see Directness, below).

Precision: The evidence has moderate precision.

- The body of evidence had 7 studies, and they had sufficient statistical power to detect significant differences for many of the analyses of interest. However, an assessment of precision is hindered by the heterogeneity of the analyses.

Directness: The evidence has limited directness.

- The studies in this body of evidence were generally designed to examine the effect of novel infant formula compositions rather than the difference between infants fed human milk vs. infant formula.

Generalizability: The evidence has limited generalizability.

- Participants’ exposure years were from the early 1980s to 2002. Therefore, the findings may not be generalizable to infants who consume formulas currently on the market.
- Only 2 studies reported race or ethnicity, which was 100% White (this was an inclusion criterion for study eligibility).^14,15^ In addition, 4 studies, from the same research group, included different participants who likely represented the same population of infants in Australia.^4,13,15^

Risk of bias: There is a limited likelihood that the design and conduct of the studies have prevented or minimized bias.

- None of the studies controlled for any of the key confounders on the analytic framework. These studies were all described by the study authors as randomized controlled trials (to test the effects of different infant formula compositions on infant outcomes), and successful randomization minimizes bias from confounding. However, the data of interest for this systematic review are the comparisons of the randomized formula-fed groups to non-randomized infants fed human milk; therefore, there is a risk of bias from confounding.
- The studies were prone to other risks of bias (Table 16), which varied between studies.

In addition to the graded elements of the assessment of the evidence, above, publication bias may be a concern because the body of evidence consisted of a small number of studies that all reported significant associations.

Table 15 Evidence examining the relationship between ever vs never consuming human milk and fatty acid status^*^

Article; Study design; Country | Ever vs never consuming human milk exposure^†^ | Fatty acid status outcome^‡^ | Significant associations | Nonsignificant associations
Gibson 2005 ^4^; NRCT; Australia | Control FF vs BF | Erythrocyte:
Gibson 2005 ^4^; NRCT; Australia | Control FF vs BF | Total SFA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 42.0 ± 0.1 vs 42.4 ± 0.1, p<0.01 | .
| | Total MUFA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 18.2 ± 0.1 vs 17.2 ± 0.1, p<0.01 | .
| | Total n-6 (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 35.4 ± 0.1 vs 31.8 ± 0.2, p<0.01 | .
| | 18:2n-6 LA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 12.8 ± 0.1 vs 10.1 ± 0.2, p<0.01 | .
| | 20:3n-6 DGLA (mean ± SEM, % of total RBCmembrane FA) @ 7 mo (N=69, 96) | 1.9 ± 0.04 vs 1.6 ± 0.03, p<0.01 | .
| | 20:4n-6 AA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 14.5 ± 0.1 vs 15.3 ± 0.1, p<0.01 | .
| | 22:4n-6 AdA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 4.7 ± 0.04 vs 3.7 ± 0.06, p<0.01 | .
| | Total n-3 (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 3.9 ± 0.07 vs 7.8 ± 0.2, p<0.01 | .
| | 20:5n-3 EPA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 0.2 ± 0.01 vs 0.4 ± 0.02, p<0.01 | .
| | 22:5n-3 DPA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 1.6 ± 0.03 vs 2.2 ± 0.05, p<0.01 | .
| | 22:6n-3 DHA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=69, 96) | 2.1 ± 0.05 vs 4.9 ± 0.18, p<0.01 | .
| Nucleotide-supplemented FF vs BF | Erythrocyte:
| Nucleotide-supplemented FF vs BF | Total SFA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 42.0 ± 0.1 vs 42.4 ± 0.1, p<0.01 | .
| | Total MUFA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 18.2 ± 0.1 vs 17.2 ± 0.1, p<0.01 | .
| | Total n-6 (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 35.3 ± 0.2 vs 31.8 ± 0.2, p<0.01 | .
| | 18:2n-6 LA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 12.8 ± 0.1 vs 10.1 ± 0.2, p<0.01 | .
| | 20:3n-6 DGLA (mean ± SEM, % of total RBCmembrane FA) @ 7 mo (N=67, 96) | 1.9 ± 0.1 vs 1.6 ± 0.03, p<0.01 | .
| | 20:4n-6 AA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 14.4 ± 0.1 vs 15.3 ± 0.1, p<0.01 | .
| | 22:4n-6 AdA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 4.7 ± 0.05 vs 3.7 ± 0.06, p<0.01 | .
| | Total n-3 (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 4.0 ± 0.07 vs 7.8 ± 0.2, p<0.01 | .
| | 20:5n-3 EPA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 0.2 ± 0.01 vs 0.4 ± 0.02, p<0.01 | .
| | 22:5n-3 DPA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 1.6 ± 0.03 vs 2.2 ± 0.05, p<0.01 | .
| | 22:6n-3 DHA (mean ± SEM, % of total RBC membrane FA) @ 7 mo (N=67, 96) | 2.1 ± 0.04 vs 4.9 ± 0.18, p<0.01 | .
Gil 1986 ^5^; NRCT; Spain | EBF vs Conventional FF | Plasma:
Gil 1986 ^5^; NRCT; Spain | EBF vs Conventional FF | 12:0 Lauric (mean ± SE, g/100 ml of total FA)
Gil 1986 ^5^; NRCT; Spain | EBF vs Conventional FF | @ 1 wk (N=26, 35) | . | 0.70 ± 0.15 vs. 0.37 ± 0.18; NS
| | @ 4 wk (N=26, 35) | . | 1.43 ± 1.03 vs 0.57 ± 0.27; NS
| | 14:0 Myristic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 35) | . | 1.65 ± 0.17 vs 1 .37 ± 0.23; NS
| | @ 4 wk (N=26, 35) | . | 1.45 ± 0.31 vs 1.14 ± 0.23; NS
| | 16:0 Palmitic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 35) | . | 30.31 ± 1.18 vs 28.69 ± 1.25; NS
| | @ 4 wk (N=26, 35) | . | 28.67 ± 1.42 vs 26.95 ± 0.92; NS
| | 16:1 (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 35) | 2.15 ±0.29 vs 3.47 ± 0.61; p<0.05 | .
| | @ 4 wk (N=26, 35) | . | 1.06 ± 0.54 vs 0.51 ± 0.30; NS
| | 18:0 Stearic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 35) | 13.13 ± 0.64 vs 9.82 ± 0.61; p<0.05 | .
| | @ 4 wk (N=26, 35) | 17.03 ± 1.42 vs 12.74 ± 0.74; p<0.05 | .
| | 18:1 (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 35) | . | 21.96 ± 1.06 vs 23.82 ± 1.45; NS
| | @ 4 wk (N=26, 35) | . | 17.34 ± 1.54 vs 19.27 ± 1.27; NS
| | 20:0 Arachidic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 35) | 0.10 ± 0.03 vs 0.38 ± 0.08; p<0.05 | .
| | @ 4 wk (N=26, 35) | . | 0.42 ± 0.33 vs 0.07 ± 0.04; NS
| | 16:1/16:0 Palmitic (mean ± SE)
| | @ 1 wk (N=26, 35) | 0.07 ± 0.01 vs 0.11 ± 0.02; p<0.05 | .
| | @ 4 wk (N=26, 35) | . | 0.04 ± 0.02 vs 0.03 ± 0.01; NS
| | 18:1/18:0 Stearic (mean ± SE)
| | @ 1 wk (N=26, 35) | 1.75 ± 0.15 vs 2.56 ± 0.32; p<0.05 | .
| | @ 4 wk (N=26, 35) | 1.23 ± 0.12 vs 1.55 ± 0.11; p<0.05 | .
| | 18:1/18:2 (mean ± SE)
| | @ 1 wk (N=26, 35) | 1.72 ± 0.14 vs 1.38 ± 0.17; p<0.05 | .
| | @ 4 wk (N=26, 35) | 1.12 ± 0.12 vs 0.74 ± 0.05; p<0.05 | .
| | 20:4/18:2 (mean ± SE)
| | @ 1 wk (N=26, 35) | 0.91 ± 0.13 vs 0.60 ± 0.12; p<0.05 | .
| | @ 4 wk (N=26, 35) | 0.41 ± 0.04 vs 0.22 ± 0.03; p<0.05 | .
| | 18:3+20:3/20:4 (mean ± SE)
| | @ 1 wk (N=26, 35) | . | 0.10 ± 0.02 vs 0.08 ± 0.03; NS
| | @ 4 wk (N=26, 35) | 0.09 ± 0.04 vs 0.80 ± 0.22; p<0.05 | .
| EBF vs Nucleotide-supplemented FF | Plasma:
| EBF vs Nucleotide-supplemented FF | 12:0 Lauric (mean ± SE, g/100 ml of total FA)
| EBF vs Nucleotide-supplemented FF | @ 1 wk (N=26, 23) | . | 0.70 ± 0.15 vs. 0.73 ± 0.42; NS
| | @ 4 wk (N=26, 23) | . | 1.43 ± 1.03 vs 0.09 ± 0.07; NS
| | 14:0 Myristic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 23) | . | 1.65 ± 0.17 vs 1.50 ± 0.18; NS
| | @ 4 wk (N=26, 23) | . | 1.45 ± 0.31 vs 1.11 ± 0.24; NS
| | 16:0 Palmitic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 23) | . | 30.31 ± 1.18 vs 30.94 ± 3.85; NS
| | @ 4 wk (N=26, 23) | . | 28.67 ± 1.42 vs 28.37 ± 1.72; NS
| | 16:1 (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 23) | . | 2.15 ±0.29 vs 2.14 ± 0.67; NS
| | @ 4 wk (N=26, 23) | . | 1.06 ± 0.54 vs 0.93 ± 0.29; NS
| | 18:0 Stearic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 23) | . | 13.13 ± 0.64 vs 13.86 ± 1.67; NS
| | @ 4 wk (N=26, 23) | . | 17.03 ± 1.42 vs 15.15 ± 1.16; NS
| | 18:1 (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 23) | . | 21.96 ± 1.06 vs 20.85 ± 1.17; NS
| | @ 4 wk (N=26, 23) | . | 17.34 ± 1.54 vs 17.61 ± 1.30; NS
| | 20:0 Arachidic (mean ± SE, g/100 ml of total FA)
| | @ 1 wk (N=26, 23) | . | 0.10 ± 0.03 vs 0.17 ± 0.07; NS
| | @ 4 wk (N=26, 23) | . | 0.42 ± 0.33 vs 0.11 ± 0.03; NS
| | 16:1/16:0 Palmitic (mean ± SE)
| | @ 1 wk (N=26, 35) | . | 0.07 ± 0.01 vs 0.07 ± 0.02; NS
| | @ 4 wk (N=26, 35) | . | 0.04 ± 0.02 vs 0.03 ± 0.01; NS
| | 18:1/18:0 Stearic (mean ± SE)
| | @ 1 wk (N=26, 35) | . | 1.75 ± 0.15 vs 1.60 ± 0.26; NS
| | @ 4 wk (N=26, 35) | . | 1.23 ± 0.12 vs 1.33 ± 0.13; NS
| | 18:1/18:2 (mean ± SE)
| | @ 1 wk (N=26, 35) | 1.72 ± 0.14 vs 1.27 ± 0.17; p<0.05 | .
| | @ 4 wk (N=26, 35) | . | 1.12 ± 0.12 vs 0.95 ± 0.16; NS
| | 20:4/18:2 (mean ± SE)
| | @ 1 wk (N=26, 35) | 0.91 ± 0.13 vs 0.42 ± 0.16; p<0.05 | .
| | @ 4 wk (N=26, 35) | . | 0.41 ± 0.04 vs 0.41 ± 0.05; NS
| | 18:3+20:3/20:4 (mean ± SE)
| | @ 1 wk (N=26, 35) | . | 0.10 ± 0.02 vs 0.03 ± 0.03; NS
| | @ 4 wk (N=26, 35) | 0.09 ± 0.04 vs 0.17 ± 0.06; p<0.05 | .
Innis 1997 ^6^; NRCT; U.S. & Canada | EBF vs Standard FF | Plasma phospholipid:
Innis 1997 ^6^; NRCT; U.S. & Canada | EBF vs Standard FF | 16:0 palmitic (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 23.9 ± 0.3 vs 26.6 ± 0.3; p<0.05 | .
| | 18:0 stearic (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 17.8 ± 0.3 vs 16.8 ± 0.3; p<0.05 | .
| | 18:1 (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 12.2 ± 0.4 vs 13.9 ± 0.4; p<0.05 | .
| | 18:3n-3 ALA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | . | 0.2 ± 0.0 vs 0.2 ± 0.0; NS
| | 20:5n-3 EPA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 0.3 ± 0.0 vs 0.1 ± 0.0; p<0.05 | .
| | 22:5n-3 DPA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 0.9 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | 22:6n-3 DHA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 3.8 ± 0.1 vs 1.4 ± 0.1; p<0.05 | .
| | 18:2n-6 LA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 22.8 ± 0.6 vs 28.7 ± 0.5; p<0.05 | .
| | 20:2n-6 Eicosadienoic (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | . | 0.4 ± 0.0 vs 0.3 ± 0.0; NS
| | 20:3n-6 DGLA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 2.8 ± 0.1 vs 2.2 ± 0.1; p<0.05 | .
| | 20:4n-6 AA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 12.2 ± 0.3 vs 6.6 ± 0.2; p<0.05 | .
| | 22:4n-6 AdA (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 0.5 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | 22:5n-6 (mean ± SEM, wt% total FA) @ 90 d (N=54, 58) | 0.5 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | Erythrocyte phosphatidylcholine:
| | 16:0 Palmitic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 31.8 ± 0.4 vs 33.6 ± 0.4; p<0.05 | .
| | 18:0 Stearic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 14.2 ± 0.2 vs 13.0 ± 0.2; p<0.05 | .
| | 18:1 (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 20.1 ± 0.4 vs 20.0 ± 0.4; NS
| | 18:3n-3 ALA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 0.2 ± 0.0 vs 0.3 ± 0.0; NS
| | 20:5n-3 EPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.2 ± 0.0 vs 0.1 ± 0.0; p<0.05 | .
| | 22:5n-3 DPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.4 ± 0.0 vs 0.2 ± 0.0; p<0.05 | .
| | 22:6n-3 DHA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 1.6 ± 0.1 vs 0.6 ± 0.1; p<0.05 | .
| | 18:2n-6 LA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 18.5 ± 09.4^§^ vs 23.0 ± 0.4; p<0.05 | .
| | 20:2n-6 Eicosadienoic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 0.5 ± 0.0 vs 0.5 ± 0.0; NS
| | 20:3n-6 DGLA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 2.0 ± 0.1 vs 1.6 ± 0.1; p<0.05 | .
| | 20:4n-6 AA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 7.7 ± 0.3 vs 4.5 ± 0.3; NS
| | 22:4n-6 AdA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 0.5 ± 0.1 vs 0.4 ± 0.1; NS
| | 22:5n-6 (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 0.2 ± 0.0 vs 0.2 ± 0.0; NS
| | Erythrocyte phosphatidylethanolamine:
| | 16:0 Palmitic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 14.3 ± 0.3 vs 14.9 ± 0.3; NS
| | 18:0 Stearic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 8.1 ± 0.3 vs 8.1 ± 0.2; NS
| | 18:1 (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 20.3 ± 0.5 vs 22.0 ± 0.4; p<0.05 | .
| | 18:3n-3 ALA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 0.3 ± 0.0 vs 0.4 ± 0.0; NS
| | 20:5n-3 EPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.5 ± 0.0 vs 0.3 ± 0.0; p<0.05 | .
| | 22:5n-3 DPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 2.9 ± 0.1 vs 2.0 ± 0.1; p<0.05 | .
| | 22:6n-3 DHA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 6.9 ± 0.2 vs 4.0 ± 0.2; p<0.05 | .
| | 18:2n-6 LA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 6.7 ± 0.3 vs 9.0 ± 0.3; p<0.05 | .
| | 20:2n-6 Eicosadienoic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.4 ± 0.0 vs 0.5 ± 0.0; p<0.05 | .
| | 20:3n-6 DGLA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 1.5 ± 0.0 vs 2.0 ± 0.0; p<0.05 | .
| | 20:4n-6 AA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 25.9 ± 0.6 vs 23.9 ± 0.2; p<0.05 | .
| | 22:4n-6 AdA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 8.2 ± 0.2 vs 8.7 ± 0.2; NS
| | 22:5n-6 (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 1.5 ± 0.1 vs 1.5 ± 0.1; NS
| EBF vs LA and ALA supplemented FF | Plasma phospholipid:
| EBF vs LA and ALA supplemented FF | 16:0 Palmitic (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | . | 23.9 ± 0.3 vs 23.5 ± 0.3; NS
| | 18:0 Stearic (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 17.8 ± 0.3 vs 19.9 ± 0.3; p<0.05 | .
| | 18:1 (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 12.2 ± 0.4 vs 7.8 ± 0.4; p<0.05 | .
| | 18:3n-3 ALA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 0.2 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | 20:5n-3 EPA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 0.3 ± 0.0 vs 0.2 ± 0.0; p<0.05 | .
| | 22:5n-3 DPA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 0.9 ± 0.0 vs 0.6 ± 0.09; p<0.05 | .
| | 22:6n-3 DHA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 3.8 ± 0.1 vs 1.7 ± 0.1; p<0.05 | .
| | 18:2n-6 LA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 22.8 ± 0.6 vs 34.3 ± 0.5; p<0.05 | .
| | 20:2n-6 Eicosadienoic (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 0.4 ± 0.0 vs 0.6 ± 0.0; p<0.05 | .
| | 20:3n-6 DGLA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 2.8 ± 0.1 vs 1.8 ± 0.1; p<0.05 | .
| | 20:4n-6 AA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 12.2 ± 0.3 vs 6.8 ± 0.3; p<0.05 | .
| | 22:4n-6 AdA (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 0.5 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | 22:5n-6 (mean ± SEM, wt% total FA) @ 90 d (N=54, 57) | 0.5 ± 0.0 vs 0.2 ± 0.0; p<0.05 | .
| | Erythrocyte phosphatidylcholine:
| | 16:0 Palmitic (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | . | 31.8 ± 0.4 vs 30.9 ± 0.4; NS
| | 18:0 Stearic (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 14.2 ± 0.2 vs 16.1 ± 0.2; p<0.05 | .
| | 18:1 (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 20.1 ± 0.4 vs 15.2 ± 0.4; p<0.05 | .
| | 18:3n-3 ALA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 0.2 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | 20:5n-3 EPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 0.2 ± 0.0 vs 0.1 ± 0.0; p<0.05 | .
| | 22:5n-3 DPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 0.4 ± 0.0 vs 0.3 ± 0.0; p<0.05 | .
| | 22:6n-3 DHA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 1.6 ± 0.1 vs 0.7 ± 0.1; p<0.05 | .
| | 18:2n-6 LA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 18.5 ± 09.4^§^ vs 27.3 ± 0.4; p<0.05 | .
| | 20:2n-6 Eicosadienoic (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 0.5 ± 0.0 vs 0.8 ± 0.0; p<0.05 | .
| | 20:3n-6 DGLA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 2.0 ± 0.1 vs 1.2 ± 0.1; p<0.05 | .
| | 20:4n-6 AA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 7.7 ± 0.3 vs 4.4 ± 0.3; p<0.05 | .
| | 22:4n-6 AdA (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | . | 0.5 ± 0.1 vs 0.4 ± 0.1; NS
| | 22:5n-6 (mean ± SEM, wt% total FA) @ 90 d (N=55, 57) | 0.2 ± 0.0 vs 0.1 ± 0.0; p<0.05 | .
| | Erythrocyte phosphatidylethanolamine:
| | 16:0 Palmitic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 14.3 ± 0.3 vs 15.4 ± 0.3; p<0.05 | .
| | 18:0 Stearic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 8.1 ± 0.3 vs 9.9 ± 0.2; p<0.05 | .
| | 18:1 (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 20.3 ± 0.5 vs 18.6 ± 0.4; p<0.05 | .
| | 18:3n-3 ALA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.3 ± 0.0 vs 0.6 ± 0.0; p<0.05 | .
| | 20:5n-3 EPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.5 ± 0.0 vs 0.4 ± 0.0; p<0.05 | .
| | 22:5n-3 DPA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 2.9 ± 0.1 vs 2.9 ± 0.1; NS
| | 22:6n-3 DHA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 6.9 ± 0.2 vs 4.0 ± 0.2; p<0.05 | .
| | 18:2n-6 LA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 6.7 ± 0.3 vs 12.0 ± 0.3; p<0.05 | .
| | 20:2n-6 Eicosadienoic (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 0.4 ± 0.0 vs 0.9 ± 0.0; p<0.05 | .
| | 20:3n-6 DGLA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 1.5 ± 0.0 vs 1.8 ± 0.0; p<0.05 | .
| | 20:4n-6 AA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 25.9 ± 0.6 vs 22.2 ± 0.5; p<0.05 | .
| | 22:4n-6 AdA (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | . | 8.2 ± 0.2 vs 7.8 ± 0.2; NS
| | 22:5n-6 (mean ± SEM, wt% total FA) @ 90 d (N=55, 58) | 1.5 ± 0.1 vs 1.1 ± 0.1; p<0.05 | .
Kohn 1994 ^10^; NRCT; NR (Germany or Belgium) | BF vs Conventional FF | Plasma phospholipid:
Kohn 1994 ^10^; NRCT; NR (Germany or Belgium) | BF vs Conventional FF | 20:4n-6 AA (median wt% of total FA)
Kohn 1994 ^10^; NRCT; NR (Germany or Belgium) | BF vs Conventional FF | @ 7 d (N=NR, NR) | ~14 vs ~8; p<0.05 | .
| | @ 30 d (N=NR, NR) | ~12 vs ~7; p<0.05 | .
| | @ 90 d (N=NR, NR) | . | ~8 vs ~7; NS
| | 22:6n-3 DHA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~4 vs ~3; NS
| | @ 30 d (N=NR, NR) | ~4 vs ~2; p<0.05 | .
| | @ 90 d (N=NR, NR) | ~3 vs ~1; p<0.05 | .
| | Erythrocyte phosphatidylcholine
| | 20:4n-6 AA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | ~14 vs ~10; p<0.05 | .
| | @ 30 d (N=NR, NR) | ~9 vs ~5; p<0.05 | .
| | @ 90 d (N=NR, NR) | . | ~7 vs ~4; NS
| | 22:6n-3 DHA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~3 vs ~2; NS
| | @ 30 d (N=NR, NR) | ~3 vs ~2; p<0.05 | .
| | @ 90 d (N=NR, NR) | ~3 vs ~1; p<0.05 | .
| | Erythrocyte phosphatidylethanolamine:
| | 20:4n-6 AA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~26 vs ~26; NS
| | @ 30 d (N=NR, NR) | . | ~26 vs ~24; NS
| | @ 90 d (N=NR, NR) | . | ~26 vs ~26; NS
| | 22:6n-3 DHA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~12 vs ~12; NS
| | @ 30 d (N=NR, NR) | . | ~12 vs ~11; NS
| | @ 90 d (N=NR, NR) | ~12 vs ~6; p<0.05 | .
| BF vs AA- and DHA-supplemented FF | Plasma phospholipid:
| BF vs AA- and DHA-supplemented FF | 20:4n-6 AA (median wt% of total FA)
| BF vs AA- and DHA-supplemented FF | @ 7 d (N=NR, NR) | ~14 vs ~12; p<0.05 | .
| | @ 30 d (N=NR, NR) | . | ~12 vs ~11; NS
| | @ 90 d (N=NR, NR) | . | ~8 vs ~10; NS
| | 22:6n-3 DHA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~4 vs ~4; NS
| | @ 30 d (N=NR, NR) | . | ~4 vs ~3; NS
| | @ 90 d (N=NR, NR) | . | ~3 vs ~3; NS
| | Erythrocyte phosphatidylcholine:
| | 20:4n-6 AA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | ~14 vs ~11; p<0.05 | .
| | @ 30 d (N=NR, NR) | . | ~9 vs ~7; NS
| | @ 90 d (N=NR, NR) | . | ~7 vs ~7; NS
| | 22:6n-3 DHA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~3 vs ~3; NS
| | @ 30 d (N=NR, NR) | . | ~3 vs ~2; NS
| | @ 90 d (N=NR, NR) | . | ~3 vs ~2; NS
| | Erythrocyte phosphatidylethanolamine:
| | 20:4n-6 AA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~26 vs ~26; NS
| | @ 30 d (N=NR, NR) | . | ~26 vs ~25; NS
| | @ 90 d (N=NR, NR) | . | ~27 vs ~27; NS
| | 22:6n-3 DHA (median wt% of total FA)
| | @ 7 d (N=NR, NR) | . | ~12 vs ~11; NS
| | @ 30 d (N=NR, NR) | . | ~12 vs ~12; NS
| | @ 90 d (N=NR, NR) | . | ~12 vs ~11; NS
Makrides 1995 ^13^; NRCT; Australia | BF vs Placebo FF | Erythrocyte:
Makrides 1995 ^13^; NRCT; Australia | BF vs Placebo FF | 18:2n-6 LA (mean ± SD, % total FA):
Makrides 1995 ^13^; NRCT; Australia | BF vs Placebo FF | @ 6 wk (N=21, 18) | 8.5 ± 0·8 vs 11.9 ± 1.0; p<0.05 | .
| | @ 16 wk (N=21, 18) | 8.7 ± 0·9 vs 11.7 ± 1.0; p<0.05 | .
| | @ 30 wk (N=21, 18) | 9.3 ± 1·4 vs 13.1 ± 1.3; p<0.05 | .
| | 20:4n-6 AA (mean ± SD, % total FA)
| | @ 6 wk (N=21, 18) | 14.1 ± 1.4 vs 11.8 ± 1.2; p<0.05 | .
| | @ 16 wk (N=21, 18) | 15.1 ± 1.4 vs 12.9 ± 1.3; p<0.05 | .
| | @ 30 wk (N=21, 18) | 14.6 ± 2.5 vs 13.7 ± 1.1; p<0.05 | .
| | 20:5n-3 EPA (mean ± SD, % total FA)
| | @ 6 wk (N=21, 18) | . | 0.2 ± 0.1 vs 0.1 ± 0.1; NS
| | @ 16 wk (N=21, 18) | 0.3 ± 0.1 vs 0.2 ± 0.1; p<0.05 | .
| | @ 30 wk (N=21, 18) | 0.3 ± 0.2 vs 0.2 ± 0.1; p<0.05 | .
| | 22:6n-3 DHA (mean ± SD, % total FA)
| | @ 6 wk (N=21, 18) | 5.5 ± 0.8 vs 4.2 ± 0.7; p<0.05 | .
| | @ 16 wk (N=21, 18) | 5.5 ± 1.0 vs 2.5 ± 0.3; p<0.05 | .
| | @ 30 wk (N=21, 18) | 4.7 ± 1.4 vs 2.0 ± 0.4; p<0.05 | .
| BF vs DHA-supplemented FF | Erythrocyte:
| BF vs DHA-supplemented FF | 18:2n-6 LA (mean ± SD, % total FA)
| BF vs DHA-supplemented FF | @ 6 wk (N=21, 12) | 8.5 ± 0.8 vs 10.7 ± 1.1; p<0.05 | .
| | @ 16 wk (N=21, 12) | 8.7 ± 0.9 vs 10.5 ± 0.6; p<0.05 | .
| | @ 30 wk (N=21, 12) | 9.3 ± 1.4 vs 11.3 ± 0.6; p<0.05 | .
| | 20:4n-6 AA (mean ± SD, % total FA)
| | @ 6 wk (N=21, 12) | 14.1 ± 1.4 vs 10.9 ± 1.8; p<0.05 | .
| | @ 16 wk (N=21, 12) | 15.1 ± 1.4 vs 10.2 ± 1.0; p<0.05 | .
| | @ 30 wk (N=21, 12) | 14.6 ± 2.5 vs 10.5 ± 1.0; p<0.05 | .
| | 20:5n-3 EPA (mean ± SD, % total FA)
| | @ 6 wk (N=21, 12) | 0.2 ± 0.1 vs 1.2 ± 0.2; p<0.05 | .
| | @ 16 wk (N=21, 12) | 0.3 ± 0.1 vs 1.9 ± 0.2; p<0.05 | .
| | @ 30 wk (N=21, 12) | 0.3 ± 0.2 vs 2.1 ± 0.2; p<0.05 | .
| | 22:6n-3 DHA (mean ± SD, % total FA)
| | @ 6 wk (N=21, 12) | . | 5.5 ± 0.8 vs 5.4 ± 1.1; NS
| | @ 16 wk (N=21, 12) | 5.5 ± 1.0 vs 6.3 ± 0.7; p<0.05 | .
| | @ 30 wk (N=21, 12) | 4.7 ± 1.4 vs 6.3 ± 0.7; p<0.05 | .
Makrides 1999 ^15^; NRCT; Australia | BF vs Placebo FF | Plasma phospholipid:
Makrides 1999 ^15^; NRCT; Australia | BF vs Placebo FF | Total SFA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 43.8 ± 0.9 vs 45.0 ± 0.6; p<0.001 | .
| | Total MUFA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | . | 12.0 ± 1.2 vs 11.9 ± 0.7; NS
| | 18:1n-9 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 8.5 ± 1.1 vs 9.1 ± 0.6; p>0.001 | .
| | Total n-6 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 36.4 ± 1.5 vs 39.6 ± 0.9; p<0.001 | .
| | 18:2n-6 LA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 20.4 ± 2.5 vs 27.7 ± 1.9; p<0.01 | .
| | 20:3n-6 DGLA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | . | 2.9 ± 0.4 vs 2.8 ± 0.5; NS
| | 20:4n-6 AA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 11.9 ± 1.6 vs 7.7 ± 1.2; p<0.001 | .
| | 22:4n-6 AdA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 0.49 ± 0.09 vs 0.50 ± 0.07; p<0.001 | .
| | 22:5n-6 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 0.38 ± 0.10 vs 0.56 ± 0.14; p<0.001 | .
| | Total n-3 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 6.3 ± 1.0 vs 3.1 ± 0.6; p<0.001 | .
| | 20:5n-3 EPA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 0.41 ± 0.27 vs 0.22 ± 0.06; p<0.001 | .
| | 22:5n-3 DPA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 1.20 ± 0.19 vs 0.71 ± 0.18; p<0.001 | .
| | 22:6n-3 DHA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 20) | 4.7 ± 0.8 vs 2.0 ± 0.5; p<0.001 | .
| BF vs DHA-supplemented FF | Plasma phospholipid:
| BF vs DHA-supplemented FF | Total SFA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 43.8 ± 0.9 vs 45.3 ± 0.7; p<0.001 | .
| | Total MUFA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | . | 12.0 ± 1.2 vs 11.8 ± 0.5; NS
| | 18:1n-9 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 8.5 ± 1.1 vs 9.1 ± 0.9; p<0.001 | .
| | Total n-6 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 36.4 ± 1.5 vs 35.2 ± 1.2; p<0.001 | .
| | 18:2n-6 LA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 20.4 ± 2.5 vs 26.3 ± 1.7; p<0.001 | .
| | 20:3n-6 DGLA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 2.9 ± 0.4 vs 2.3 ± 0.4; p<0.001 | .
| | 20:4n-6 AA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 11.9 ± 1.6 vs 5.9 ± 1.2; p<0.001 | .
| | 22:4n-6 AdA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 0.49 ± 0.09 vs 0.25 ± 0.04; p<0.001 | .
| | 22:5n-6 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 0.38 ± 0.10 vs 0.25 ± 0.04; p<0.001 | .
| | Total n-3 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 6.3 ± 1.0 vs 7.1 ± 0.7; p<0.001 | .
| | 20:5n-3 EPA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | . | 0.41 ± 0.27 vs 0.51 ± 0.11; NS
| | 22:5n-3 DPA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 1.20 ± 0.19 vs 0.58 ± 0.09; p<0.001 | .
| | 22:6n-3 DHA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 4.7 ± 0.8 vs 6.0 ± 0.6; p<0.001 | .
| BF vs DHA- and AAsupplemented FF | Plasma phospholipid:
| BF vs DHA- and AAsupplemented FF | Total SFA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 43.8 ± 0.9 vs 45.2 ± 0.5; p<0.001 | .
| | Total MUFA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 12.0 ± 1.2 vs 10.4 ± 0.5; p<0.001 | .
| | 18:1n-9 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 8.5 ± 1.1 vs 7.9 ± 0.6; p<0.001 | .
| | Total n-6 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 36.4 ± 1.5 vs 37.5 ± 1.2; p<0.001 | .
| | 18:2n-6 LA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 20.4 ± 2.5 vs 24.1 ± 1.3; p<0.001 | .
| | 20:3n-6 DGLA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 2.9 ± 0.4 vs 2.0 ± 0.4; p<0.001 | .
| | 20:4n-6 AA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 11.9 ± 1.6 vs 10.3 ± 0.7; p<0.001 | .
| | 22:4n-6 AdA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 0.49 ± 0.09 vs 0.39 ± 0.07; p<0.001 | .
| | 22:5n-6 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 0.38 ± 0.10 vs 0.44 ± 0.10; p<0.001 | .
| | Total n-3 (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | . | 6.3 ± 1.0 vs 6.3 ± 0.7; NS
| | 20:5n-3 EPA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 0.41 ± 0.27 vs 0.18 ± 0.04; p<0.001 | .
| | 22:5n-3 DPA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 1.20 ± 0.19 vs 0.37 ± 0.07; p<0.001 | .
| | 22:6n-3 DHA (mean ± SD, % total phospholipid FA) @ 16 wk (N=32, 23) | 4.7 ± 0.8 vs 5.7 ± 0.7; p<0.001 | .
Makrides 2000 ^14^; NRCT; Australia | BF vs 10:1 LA:ALA FF | Plasma phospholipid:
Makrides 2000 ^14^; NRCT; Australia | BF vs 10:1 LA:ALA FF | Total SFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 44.1 ± 0.8 vs 43.2 ± 0.8; p<0.005 | .
| | Total MUFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 12.5 ± 1.2 vs 13.6 ± 0.5; p<0.005 | .
| | Total n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 35.3 ± 1.6 vs 38.0 ± 1.0; p<0.005 | .
| | 18:2n-6 LA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 19.4 ± 2.0 vs 27.5 ± 1.7; p<0.005 | .
| | 20:3n-6 DGLA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 3.0 ± 0.5 vs 2.5 ± 0.4; p<0.005 | .
| | 20:4n-6 AA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 11.6 ± 1.2 vs 6.9 ± 0.9; p<0.005 | .
| | 22:4n-6 AdA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 0.49 ± 0.07 vs 0.42 ± 0.07; p<0.005 | .
| | 22:5n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | . | 0.38 ± 0.09 vs 0.35 ± 0.08; NS
| | Total n-3 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 6.1 ± 0.9 vs 3.1 ± 0.5; p<0.005 | .
| | 18:3n-3 ALA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 0.13 ± 0.05 vs 0.20 ± 0.03; p<0.005 | .
| | 20:5n-3 EPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 0.41 ± 0.14 vs 0.25 ± 0.11; p<0.005 | .
| | 22:5n-3 DPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 1.2 ± 0.2 vs 0.8 ± 0.2; p<0.005 | .
| | 22:6n-3 DHA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 4.4 ± 0.7 vs 1.9 ± 0.3; p<0.005 | .
| | Erythrocyte phospholipid:
| | Total SFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 43.0 ± 0.8 vs 42.4 ± 0.7; p<0.005 | .
| | Total MUFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 16.6 ± 1.1 vs 17.5 ± 0.8; p<0.005 | .
| | Total n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 30.3 ± 1.2 vs 32.8 ± 0.6; p<0.005 | .
| | 18:2n-6 LA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 7.8 ± 0.8 vs 11.1 ± 0.8; p<0.005 | .
| | 20:3n-6 DGLA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | . | 1.7 ± 0.3 vs 1.8 ± 0.4; NS
| | 20:4n-6 AA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 16.1 ± 0.8 vs 14.8 ± 0.7; p<0.005 | .
| | 22:4n-6 AdA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 3.6 ± 0.4 vs 3.9 ± 0.4; p<0.005 | .
| | 22:5n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | . | 0.9 ± 0.1 vs 0.9 ± 0.1; NS
| | Total n-3 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 8.1 ± 0.9 vs 5.2 ± 0.4; p<0.005 | .
| | 18:3n-3 ALA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | . | 0.14 ± 0.08 vs 0.15 ± 0.09; NS
| | 20:5n-3 EPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 0.38 ± 0.11 vs 0.25 ± 0.03; p<0.005 | .
| | 22:5n-3 DPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 2.2 ± 0.3 vs 1.8 ± 0.1; p<0.005 | .
| | 22:6n-3 DHA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 29) | 5.6 ± 0.7 vs 3.0 ± 0.3; p<0.005 | .
| BF vs 5:1 LA:ALA FF | Plasma phospholipid:
| BF vs 5:1 LA:ALA FF | Total SFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | . | 44.1 ± 0.8 vs 43.8 ± 0.8; NS
| | Total MUFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 12.5 ± 1.2 vs 14.1 ± 0.6; p<0.005 | .
| | Total n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 35.3 ± 1.6 vs 36.7 ± 0.8; p<0.005 | .
| | 18:2n-6 LA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 19.4 ± 2.0 vs 26.7 ± 1.5; p<0.005 | .
| | 20:3n-6 DGLA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 3.0 ± 0.5 vs 2.3 ± 0.5; p<0.005 | .
| | 20:4n-6 AA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 11.6 ± 1.2 vs 6.8 ± 0.8; p<0.005 | .
| | 22:4n-6 AdA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 0.49 ± 0.07 vs 0.37 ± 0.09; p<0.005 | .
| | 22:5n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 0.38 ± 0.09 vs 0.26 ± 0.05; p<0.005 | .
| | Total n-3 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 6.1 ± 0.9 vs 4.1 ± 0.5; p<0.005 | .
| | 18:3n-3 ALA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 0.13 ± 0.05 vs 0.35 ± 0.05; p<0.005 | .
| | 20:5n-3 EPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | . | 0.41 ± 0.14 vs 0.41 ± 0.10; NS
| | 22:5n-3 DPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 1.2 ± 0.2 vs 0.9 ± 0.2; p<0.005 | .
| | 22:6n-3 DHA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 4.4 ± 0.7 vs 2.4 ± 0.3; p<0.005 | .
| | Erythrocyte phospholipid:
| | Total SFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 43.0 ± 0.8 vs 42.4 ± 0.8; p<0.005 | .
| | Total MUFA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 16.6 ± 1.1 vs 18.5 ± 0.8; p<0.005 | .
| | Total n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 30.3 ± 1.2 vs 31.3 ± 0.9; p<0.005 | .
| | 18:2n-6 LA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 7.8 ± 0.8 vs 10.9 ± 0.6; p<0.005 | .
| | 20:3n-6 DGLA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | . | 1.7 ± 0.3 vs 1.9 ± 0.4; NS
| | 20:4n-6 AA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 16.1 ± 0.8 vs 14.1 ± 0.7; p<0.005 | .
| | 22:4n-6 AdA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | . | 3.6 ± 0.4 vs 3.4 ± 0.3; NS
| | 22:5n-6 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 0.9 ± 0.1 vs 0.7 ± 0.1; p<0.005 | .
| | Total n-3 (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 8.1 ± 0.9 vs 6.5 ± 0.4; p<0.005 | .
| | 18:3n-3 ALA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 0.14 ± 0.08 vs 0.21 ± 0.03; p<0.005 | .
| | 20:5n-3 EPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 0.38 ± 0.11 vs 0.44 ± 0.07; p<0.005 | .
| | 22:5n-3 DPA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 2.2 ± 0.3 vs 2.4 ± 0.2; p<0.005 | .
| | 22:6n-3 DHA (mean ± SD % of total phospholipid FA) @ 16 wk (N=61, 28) | 5.6 ± 0.7 vs 3.5 ± 0.3; p<0.005 | .

* Abbreviations: AA – arachidonic acid, AdA – Adrenic acid, ALA – alpha linoleic acid, BF – breastfed/breastfeeding, DGLA – di-homo-g-linoleic acid, DHA – docosahexanoic acid, DPA – docosapentaenoic acid, EBF – exclusively breastfed/exclusive breastfeeding, EPA – eicosapentaenoic acid, FA – fatty acids, Fe – iron, FF – formula fed/formula feeding, LA – linoleic acid, MUFA – monounsaturated fatty acids/total monosaturates, N – analytic sample size, n-3 – omega-3, n-6 – omega 6, NR – not reported, NRCT – non-randomized controlled trial, NS – nonsignificant, RBC – red blood cell, SD – standard deviation, SE – standard error, SEM – standard error of the mean, SFA- saturated fatty acid/total saturates

† Exposures, from the articles included in the body of evidence, which address ever vs never consuming human milk or vice versa

‡ Outcomes, from the articles included in the body of evidence, which address fatty acid status

§ This SEM, as reported in the article, must be a typo

Table 16 Risk of bias for non-randomized controlled trials examining the relationship between the duration of any human milk consumption among infants fed human milk and fatty acid status^*^ ^†^

Study | Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Gibson 2005 ^4^ | Serious | Low | Low | Serious | Low | Low | Low
Gil 1986 ^5^ | Serious | Low | Low | Low | No information | Low | Low
Innis 1997 ^6^ | Serious | Low | Low | Low | Moderate | Moderate | Low
Kohn 1994 ^10^ | Serious | Low | Low | No information | No information | Low | Low
Makrides 1995 ^13^ | Serious | Low | Low | Moderate | Moderate | Low | Low
Makrides 1999 ^15^ | Serious | Low | Low | Moderate | Moderate | Low | Serious
Makrides 2000 ^14^ | Serious | Low | Low | Moderate | Moderate | Low | Serious

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919.27733354 )

#### Description of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 17)

One article, published in 2008, presented evidence on the relationship between the duration of any human milk consumption and fatty acid status from birth to 24 months.^22^

Winkler et al^22^ studied a cohort of German infants from the BABYDIET study. The BABYDIET study was designed to examine whether delayed introduction of dietary gluten affects the incidence of islet autoimmunity in infants at high risk for type 1 diabetes (i.e., infants with an at-risk HLA genotype and 1^st^-degree family member with type 1 diabetes). Infants were observed from birth to 12 months. The study assessed the association between the number of weeks of any human milk feeding and erythrocyte phosphatidylcholine and phosphatidylethanolamine fatty acids at 12 months:

- Total saturated fatty acids,
- Specific saturated fatty acids (14:0, 16:0, 18:0, 20:0, 22:0, 24:0)
- Total monounsaturated fatty acids
- Specific monounsaturated fatty acids (16:1n-7, 18:1n-9, 18:1n-7, 20:1n-9, 22:1n-9, 24:1n-9)
- Total n-3 polyunsaturated fatty acids
- Specific n-3 polyunsaturated fatty acids (18:3n-3, 20:3n-3, 20:5n-3, 22:5n-3, 22:6n-3)
- Total n-6 polyunsaturated fatty acids
- Specific n-6 polyunsaturated fatty acids (18:2n-6, 18:3n-6, 20:2n-6, 20:3n-6, 20:4n-6, 22:2n-6, 22:4n-6, 22:5n-6)
- The specific n-9 polyunsaturated fatty acid 20:3n-9

The study authors reported that none of the infants were fed long-chain polyunsaturated fatty acid-supplemented infant formula.

#### Synthesis and assessment^xi^ of the evidence comparing different durations of any human milk consumption among infants fed human milk (Table 17)

Insufficient evidence is available to examine the association between the duration of any human milk consumption and fatty acid status from birth to 24 months. The body of evidence consists of a single indirect study that reported scant information from 3 of several analyses conducted.

Table 17 Evidence examining the relationship between the duration of any human milk consumption among infants fed human milk and fatty acid status^*^

Article; Study design; Country | Duration of any human milk consumption exposure^†^ | Fatty acid status outcome^‡^ | Significant associations | Nonsignificant associations
Winkler 2008 ^22^; PCS; Germany | BF duration (wk) | Erythrocyte phosphatidylethanolamine:; 20:1n-9 (mean ± SEM, wt% of all RBC membrane FAs determined), @12 mo (N=49) | Data NR^§^; p=0.005 65F | .
| | Total n-3 PUFA (mean ± SEM, wt% of all RBC membrane FAs determined), @12 mo (N=49) | Data NR; p=0.005 | .
| | 22:6n-3 DHA (mean ± SEM, wt% of all RBC membrane FAs determined), @12 mo (N=49) | Data NR; p<0.001 | .

* Abbreviations: BF – breastfed/breastfeeding, DHA – docosahexanoic acid, FA – fatty acids, N – analytic sample size, n-3 – omega-3, NR – not reported, PCS – prospective cohort study, PUFA – polyunsaturated fatty acids, RBC – red blood cell, SEM – standard error of the mean

† Exposures, from the articles included in the body of evidence, which address the duration of any human milk consumption among infants fed human milk

‡ Outcomes, from the articles included in the body of evidence, which address fatty acid status

§ The direction of the significant association was not clearly reported.

Table 18 Risk of bias for the observational study examining the relationship between the duration of any human milk consumption among infants fed human milk and fatty acid status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing outcome data | Outcome measurement | Selection of the reported result
Winkler 2008 ^22^ | Serious | Low | Moderate | Low | Serious | Low | Serious

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

#### Description of the evidence comparing different durations of exclusive human milk consumption before the introduction of infant formula (Table 19)

One article, published in 2016, presented evidence comparing the fatty acid status of infants who consumed human milk exclusively for different durations before the introduction of infant formula.^21^

Visentin et al^21^ studied a cohort of full-term infants in Argentina fed human milk exclusively at birth. Infants fed human milk exclusively for 2 months or less were compared with infants fed human milk exclusively for 6 months or more. Infants fed human milk for 2 months or less were randomly assigned by research staff to a group fed a standard infant formula or a group fed DHA- and AA-supplemented infant formula. Erythrocyte membrane fatty acids were measured at 6 months.

#### Synthesis and assessment^xii^ of the evidence comparing different durations of exclusive human milk consumption before the introduction of infant formula (Table 19)

Insufficient evidence is available to examine the association between the duration of exclusive human milk consumption before the introduction of infant formula and fatty acid status from birth to 24 months. The body of evidence consists of a single study, which found that the associations between longer, compared with shorter, duration of exclusive human milk feeding and erythrocyte fatty acids depended on the composition of the infant formulas consumed by the infants no longer being fed human milk. For example, infants fed human milk exclusively for 6 months had significantly higher erythrocyte DHA than infants fed a standard infant formula after receiving human milk exclusively for up to 2 months, whereas there was no significant difference in erythrocyte DHA between infants fed human milk exclusively for 6 months and infants fed a DHA- and AA-supplemented infant formula after receiving human milk exclusively for up to 2 months. The study did not control for any of the key confounders on the analytic framework.

Table 19 Evidence examining the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and fatty acid status^*^

Article; Study design; Country | Duration of exclusive human milk consumption before the introduction of infant formula exposure^†^ | Fatty acid status outcome^‡^ | Significant associations | Nonsignificant associations
Visentin 2016 ^21^; NRCT; Argentina | EBF ≤2 mo prior to the introduction of standard infant formula vs EBF ≥6 mo | SFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | . | 42.82 ± 3.90 vs 42.86 ± 4.14; NS
| | 16:0 Palmitic (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | . | 20.71 ± 2.11 vs 22.05 ± 3.00; NS
| | 18:0 Stearic (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | . | 20.90 ± 2.09 vs 19.94 ± 3.04; NS
| | MUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | 19.86 ± 3.16 vs 16.83 ± 3.12; p≤0.0001 | .
| | 18:1n-9 cis (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | 15.52 ± 2.51 vs 13.6 ± 2.70; p≤0.05 | .
| | Total PUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | . | 38.01 ± 2.99 vs 40.22 ± 4.07; NS
| | n-3 PUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | 3.52 ± 1.29 vs 4.98 ± 1.14; p≤0.0001 | .
| | 22:6n-3 DHA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | 3.36 ± 1.29 vs 4.97 ± 1.14; p≤0.0001 | .
| | n-6 PUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | . | 34.50 ± 2.37 vs 35.24 ± 4.06; NS
| | 20:4n-6 AA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=25, 47) | . | 19.87 ± 2.11 vs 20.55 ± 2.25; NS
| EBF ≤2 mo prior to the introduction of DHA and AA supplemented infant formula vs EBF ≥6 mo | SFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | . | 43.40 ± 6.70 vs 42.86 ± 4.14; NS
| | 16:0 Palmitic (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | 24.64 ± 3.59 vs 22.05 ± 3.00; p≤0.01 | .
| | 18:0 Stearic (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | 17.83 ± 3.64 vs 19.94 ± 3.04; p≤0.05 | .
| | MUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | . | 17.75 ± 2.55 vs 16.83 ± 3.12; NS
| | 18:1n-9 cis (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | 15.53 ± 2.79 vs 13.6 ± 2.70; p≤0.05 | .
| | Total PUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | . | 38.89 ± 5.42 vs 40.22 ± 4.07; NS
| | n-3 PUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | . | 4.55 ± 1.60 vs 4.98 ± 1.14; NS
| | 22:6n-3 DHA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | . | 4.55 ± 1.60 vs 4.97 ± 1.14; NS
| | n-6 PUFA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | . | 34.34 ± 5.09 vs 35.24 ± 4.06; NS
| | 20:4n-6 AA (mean ± SD, % of total RBC membrane FA) @ 6 mo (N=24, 47) | 17.42 ± 3.79 vs 20.55 ± 2.25; p≤0.0001 | .

* Abbreviations: AA – arachidonic acid, DHA – docosahexanoic acid, Cu – copper, EBF – exclusively breastfed/exclusive breastfeeding, FA – fatty acids, Fe – iron, N – analytic sample size, NRCT – non-randomized controlled trial, NS – nonsignificant, RBC – red blood cell, SD – standard deviation, SFA – saturated fatty acids

† Exposures, from the articles included in the body of evidence, which address the duration of exclusive human milk consumption prior to the introduction of infant formula

‡ Outcomes, from the articles included in the body of evidence, which address fatty acid status

Table 20 Risk of bias for the observational study examining the relationship between the duration of exclusive human milk consumption before the introduction of infant formula and fatty acid status^*^ ^†^

Study | Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Visentin 2016 ^21^ | Serious | Low | Low | Low | Low | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

### Research recommendations

1. Evaluate the most useful biomarkers of nutrient status for infants and children under two years of age, and cutoff values appropriate for identifying both deficiency and excess in this age group. Nutrients of interest include those addressed in this review (iron, zinc, iodine, vitamin B12, vitamin D, and fatty acids), but may also include some that were not addressed (e.g. choline, iodine).
  Rationale: Across the body of evidence, there was heterogeneity in the methods used to assess nutrient status, in part because there is uncertainty about the most appropriate biomarkers to use in this age group. During infancy, there are profound changes in the average values of certain biomarkers between birth and 12 months, such as hemoglobin and markers of iron status, due to normal physiological changes. This makes the identification of appropriate cutoff values challenging. Serum zinc is useful as a marker of zinc status at the population level, but has serious limitations for use at the individual level. For fatty acid status, interpretation of results may differ depending on whether serum/plasma values or red blood cell values are assessed, whether samples are collected in a fed or fasted state, and on how the results are expressed (e.g. as percentage of total fatty acids, or as concentrations).
2. Measure and account for the other key factors that may play a role in studies of how infant feeding practices affect nutrient status. These factors include: birth weight, gestational age and nutrient status at birth; maternal diet and nutrient composition of her breast milk; use of nutrient supplements by mother or infant; consumption of infant formula and the fortification level of the formula; consumption of complementary foods and beverages, particularly fortified products; and other potential factors, such as exposure to sunlight (for vitamin D status), timing of umbilical cord clamping (for iron status), rate of weight gain (for iron status), and inflammation (for iron and zinc status). In addition, report the analytic group sizes and power calculations.
  Rationale: The associations between breastfeeding or formula feeding practices and nutrient status are likely to depend on all of the factors listed above, given the complex etiological pathways for each of the nutrients of interest. The evidence available is difficult to interpret because none of the studies included a comprehensive assessment of such factors. Nonsignificant associations are difficult to interpret because of a lack of information about whether all studies were sufficiently powered to examine the relationships of interest.

### Included articles

1 Amano I, Murakami A. Prevalence of infant and maternal anemia during the lactation period in Japan. Pediatrics international : official journal of the Japan Pediatric Society. 2019;61(5):495–503.doi: 10.1111/ped.13833.30895654
2 Bradley CK, Hillman L, Sherman AR, Leedy D, Cordano A. Evaluation of two iron-fortified, milk-based formulas during infancy. Pediatrics. 1993;91(5):908–914.doi.8474811
3 Cusick SE, Mei Z, Cogswell ME. Continuing anemia prevention strategies are needed throughout early childhood in low-income preschool children. The Journal of pediatrics. 2007;150(4):422–428, 428.e421–422.doi: 10.1016/j.jpeds.2007.01.004.17382124
4 Gibson RA, Hawkes JS, Makrides M. Dietary nucleotides do not alter erythrocyte long-chain polyunsaturated fatty acids in formula-fed term infants. Lipids. 2005;40(6):631–634.doi: 10.1007/s11745-005-1425-x.16149743
5 Gil A, Pita M, Martinez A, Molina JA, Sanchez Medina F. Effect of dietary nucleotides on the plasma fatty acids in at-term neonates. Human nutrition Clinical nutrition. 1986;40(3):185–195.doi.3721903
6 Innis SM, Akrabawi SS, Diersen-Schade DA, Dobson MV, Guy DG. Visual acuity and blood lipids in term infants fed human milk or formulae. Lipids. 1997;32(1):63–72.doi: 10.1007/s11745-997-0010-7.9075195
7 Isomura H, Takimoto H, Miura F, Type of milk feeding affects hematological parameters and serum lipid profile in Japanese infants. Pediatrics international : official journal of the Japan Pediatric Society. 2011;53(6):807–813.doi: 10.1111/j.1442-200X.2011.03360.x.21418403
8 Jaber L. Preventive intervention for iron deficiency anaemia in a high risk population. The International journal of risk & safety in medicine. 2014;26(3):155–162.doi: 10.3233/jrs-140622.25214161
9 Jochum F, Fuchs A, Cser A, Menzel H, Lombeck I. Trace mineral status of full-term infants fed human milk, milk-based formula or partially hydrolysed whey protein formula. The Analyst. 1995;120(3):905–909.doi: 10.1039/an9952000905.7741252
10 Kohn G, Sawatzki G, van Biervliet JP. Long-chain polyunsaturated fatty acids in infant nutrition. European journal of clinical nutrition. 1994;48 Suppl 2:S1–7.doi.
11 Lombeck I, Fuchs A. Zinc and copper in infants fed breast-milk or different formula. European journal of pediatrics. 1994;153(10):770–776.doi: 10.1007/bf01954500.7813538
12 Lönnerdal B, Chen CL. Effects of formula protein level and ratio on infant growth, plasma amino acids and serum trace elements. I. Cow’s milk formula. Acta paediatrica Scandinavica. 1990;79(3):257–265.doi: 10.1111/j.1651-2227.1990.tb11454.x.2333739
13 Makrides M, Neumann M, Simmer K, Pater J, Gibson R. Are long-chain polyunsaturated fatty acids essential nutrients in infancy? Lancet (London, England). 1995;345(8963):1463–1468.doi: 10.1016/s0140-6736(95)91035-2.
14 Makrides M, Neumann MA, Jeffrey B, Lien EL, Gibson RA. A randomized trial of different ratios of linoleic to alpha-linolenic acid in the diet of term infants: effects on visual function and growth. The American journal of clinical nutrition. 2000;71(1):120–129.doi: 10.1093/ajcn/71.1.120.10617956
15 Makrides M, Neumann MA, Simmer K, Gibson RA. Dietary long-chain polyunsaturated fatty acids do not influence growth of term infants: A randomized clinical trial. Pediatrics. 1999;104(3 Pt 1):468–475.doi: 10.1542/peds.104.3.468.10469771
16 Male C, Persson LA, Freeman V, Guerra A, van’t Hof MA, Haschke F. Prevalence of iron deficiency in 12-mo-old infants from 11 European areas and influence of dietary factors on iron status (Euro-Growth study). Acta paediatrica (Oslo, Norway : 1992). 2001;90(5):492–498.doi: 10.1080/080352501750197601.
17 Michaelsen KF, Samuelson G, Graham TW, Lonnerdal B. Zinc intake, zinc status and growth in a longitudinal study of healthy Danish infants. Acta paediatrica (Oslo, Norway : 1992). 1994;83(11):1115–1121.doi: 10.1111/j.1651-2227.1994.tb18262.x.
18 Salim S, Farquharson J, Arneil GC, Dietary copper intake in artificially fed infants. Archives of disease in childhood. 1986;61(11):1068–1075.doi: 10.1136/adc.61.11.1068.3789787
19 Thorisdottir B, Gunnarsdottir I, Steingrimsdottir L, Palsson GI, Thorsdottir I. Vitamin D intake and status in 12-month-old infants at 63-66 degrees N. Nutrients. 2014;6(3):1182–1193.doi: 10.3390/nu6031182.24662162
20 Thorsdottir I, Gunnarsson BS, Atladottir H, Michaelsen KF, Palsson G. Iron status at 12 months of age -- effects of body size, growth and diet in a population with high birth weight. European journal of clinical nutrition. 2003;57(4):505–513.doi: 10.1038/sj.ejcn.1601594.12700611
21 Visentin S, Vicentin D, Magrini G, Red blood cell membrane fatty acid composition in infants fed formulas with different lipid profiles. Early human development. 2016;100:11–15.doi: 10.1016/j.earlhumdev.2016.05.018.27391868
22 Winkler C, Hummel S, Pfluger M, The effect of maternal T1DM on the fatty acid composition of erythrocyte phosphatidylcholine and phosphatidylethanolamine in infants during early life. European journal of nutrition. 2008;47(3):145–152.doi: 10.1007/s00394-008-0708-9.18443841
23 Wu TC, Huang IF, Chen YC, Chen PH, Yang LY. Differences in serum biochemistry between breast-fed and formula-fed infants. Journal of the Chinese Medical Association : JCMA. 2011;74(11):511–515.doi: 10.1016/j.jcma.2011.09.007.22100021

ii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iii WHO Growth Standards Are Recommended for Use in the U.S. for Infants and Children 0 to 2 Years of Age. cdc.gov. https://www.cdc.gov/growthcharts/who_charts.htm#The%20WHO%20Growth%20Charts. Updated September 9, 2010. Accessed April 17, 2020.

iv Dewey KG, Chaparro CM. Session 4: Mineral metabolism and body composition iron status of breast-fed infants. The Proceedings of the Nutrition Society. 2007;66(3):412–422.17637094

v A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

vi Dewey KG, Chaparro CM. Session 4: Mineral metabolism and body composition iron status of breast-fed infants. The Proceedings of the Nutrition Society. 2007;66(3):412–422.17637094

vii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

viii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

ix A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

x A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xi A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

xii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.