# List of abbreviations

Abbreviation: Full name
BMI: Body mass index
CNPP: Center for Nutrition Policy and Promotion
FNS: USDA Food and Nutrition Service
HHS: U.S. Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
NIH: National Institutes of Health
ONGA: Office of Nutrition Guidance and Analysis
USDA: U.S. Department of Agriculture