# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statement, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^v^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 6. Nutrients from Dietary Supplements During Infancy and Toddlerhood.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders and other factors considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, key confounders, and other factors to be considered. This is the analytic framework for the systematic review examining iron from supplements consumed during infancy and toddlerhood and growth, size, body composition. The intervention or exposure of interest is consumption of iron from supplements from birth to 24 months. The comparators are consumption of iron at a different dosage or frequency from supplements, or from fortified foods. The outcomes considered include weight, length or height, weight-for-length or BMI, body circumferences, body composition, underweight, healthy weight, overweight, and obesity. The key confounders are gestational age, sex, race/ethnicity, socioeconomic status, parental education, feeding practices (e.g., human milk/infant formula history), use of foods that are fortified or rich in the nutrient of interest (in supplements studies), and anthropometry at birth or baseline. The other factors to be considered are maternal age, prenatal vitamin-supplement use, timing of cord-clamping, smoking, and maternal anthropometry.

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

This table provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics that were used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 7 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Non-randomized controlled trials, including quasi-experimental and controlled before and after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Intervention/exposure | - Studies that examine consumption of iron from supplements; - Studies that specify the dosage/amount of iron received | - Studies that do not specify the dosage/amount of iron received; - Studies that vary nutrients other than iron without controlling for that variation
Comparator | - Studies that compare consumption of iron:; ○ at a different dosage or frequency from supplements; ○ from fortified foods | - N/A
Outcomes | - Weight, weight-for-age; - Length or height, length/stature-for-age; - BMI, BMI z-score, weight-for-length; - Body circumferences e.g., head, arm, waist, thigh, neck; - Body composition and distribution e.g., % fat mass, fat-free mass, skinfold thickness; - Incidence and prevalence of:; ○ Underweight, failure to thrive, stunting, wasting; ○ Healthy weight; ○ Rapid infant weight gain; ○ Overweight; ○ Obesity | - N/A
Date of publication | - January 2000 – January 2020 | - Articles published prior to January 2000 or after January 2020
Publication status | - Articles that have been peerreviewed | - Articles that have not been peer-reviewed and are not published in peer-reviewed journals (e.g., unpublished data, manuscripts, pre-prints, reports, abstracts, and conference proceedings)
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^vi^ | - Studies conducted in countries ranked as high or higher human development | - Studies conducted in countries ranked as medium or lower human development
Study participants | - Human participants; - Males; - Females | - Non-human participants (e.g., animal studies)
Age of study participants | - Age at intervention or exposure:; ○ Infants and toddlers (birth to 24 months); - Age at outcome:; ○ Infants and toddlers (birth to 24 months); ○ Children and adolescents (2-18 years); ○ Adults (19 years and older) | - Age at intervention or exposure:; ○ Children and adolescents (2-18 years); ○ Adults (19 years and older)
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease; - Studies that enroll some participants diagnosed with a disease; - Studies that enroll some participants classified as underweight, stunted, wasted, or obese.; - Studies that enroll infants born full-term (≥37 weeks and 0/7 days gestational age) | - Studies that exclusively enroll participants diagnosed with a disease.; - Studies that exclusively enroll participants classified as underweight, stunted, wasted, or obese (i.e., studies that aim to treat participants who have already been diagnosed with the outcome of interest); - Studies that exclusively enroll infants born preterm (gestational age <37 weeks and 0/7 days), infants with low birth weight (<2500g), and/or infants born small for gestational age
Source of Foods, Beverages, or Nutrients | - Iron supplements (e.g., iron drops); - Mother’s own milk; - Commercially prepared infant formula meeting FDA^vii^ and/or Codex Alimentarius^viii^ international food standards (e.g., milk-based, soy, partially-hydrolyzed, extensive-hydrolyzed, amino acid-based); - Complementary foods/beverages | - Donor or banked milk; - Infant formulas that do not meet FDA and/or Codex Alimentarius standards

### Electronic databases and search terms

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: January 6, 2020
- Date range searched: January 1, 2000 – January 6, 2020
- Search terms:
  - #1 - iron[Mesh] OR iron compounds[Mesh] OR iron[tiab] OR ferrous[tiab] OR ferric[tiab]
  - #2 - Body Weights and Measures[Mesh] OR body weight[mh] OR obesity[tiab] OR obese[tiab] OR overweight[tiab] OR body mass index[tiab] OR BMI[tiab] OR underweight[tiab] OR wasting[tiab] OR healthy weight[tiab] OR Body Composition[Mesh] OR body composition[tiab] OR body fat[tiab] OR fat mass[tiab] OR fat free mass[tiab] OR stunting[tiab] OR stunted[tiab] OR growth charts[mh] OR growth chart*[tiab] OR Growth[Mesh:noexp] OR waist circumference[tiab] OR head circumference[tiab] OR arm circumference[tiab] OR thigh circumference[tiab] OR neck circumference[tiab] OR Anthropometry[Mesh:noexp] OR Overnutrition[Mesh] OR failure to thrive[Mesh] OR anthropometr*[tiab] OR adiposity[tiab] OR calf circumference[tiab] OR failure to thrive[tiab] OR skin fold*[tiab] OR healthy weight[tiab] OR weight for height[tiab] OR stature for age[tiab] OR weight for age[tiab] OR height for age[tiab] OR recumbent length[tiab] OR length for age[tiab] OR weight for length[tiab] OR rapid infant weight gain[tiab]
  - #3 - dietary supplements[Mesh] OR supplement*[tiab] OR drops[tiab] OR multivitamin*[tiab]
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh]))
  - #6 - #4 NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti])

Filters: Publication date from 2000/01/01 to 2020/01/06; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: January 6, 2020
- Date range searched: January 1, 2000- January 6, 2020
- Search terms:
  - #1 - [mh “iron”] OR [mh “iron compounds] OR iron OR ferrous OR ferric
  - #2 - [mh “Body Weights and Measures”] OR [mh “Body Weight”] OR obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR [mh “Body Composition”] OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR stunting OR stunted OR [mh “Growth Charts”] OR “growth chart*” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR [mh ^“Anthropometry”] OR [mh ^ “Growth”] OR [mh “Overnutrition”] OR [mh “failure to thrive”] OR anthropometr* OR adiposity OR “calf circumference” OR “failure to thrive” OR “skin fold*” OR “skin fold*” OR “normal weight” OR “healthy weight” OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “recumbent length” OR “length for age” OR “weight for length” OR “rapid infant weight gain”
  - #3 - [mh “dietary supplement”] OR supplement* OR drops OR multivitamin*
  - #4 - #1 AND #2 AND #3

Filters: Publication Year from 2000 to 2020, Trials

#### Embase

- Provider: Elsevier
- Date(s) Searched: January 6, 2020
- Date range searched: January 1, 2000 – January 6, 2020
- Search terms:
  - #1 - ‘iron’/exp OR ‘iron derivative’/exp OR ferrous:ti,ab OR ferric:ti,ab OR OR iron:ti,ab
  - #2 - ‘morphometry’/exp OR obesity:ti,ab OR obese:ti,ab OR overweight:ti,ab OR ‘body mass index’:ti,ab OR bmi:ti,ab OR underweight:ti,ab OR wasting:ti,ab OR ‘healthy weight’:ti,ab OR ‘body composition’:ti,ab OR ‘body fat’:ti,ab OR ‘fat mass’:ti,ab OR ‘fat free mass’:ti,ab OR stunting:ti,ab OR stunted:ti,ab OR ‘growth chart*’:ti,ab OR ‘waist circumference’:ti,ab OR ‘head circumference’:ti,ab OR ‘arm circumference’:ti,ab OR ‘thigh circumference’:ti,ab OR ‘neck circumference’:ti,ab OR anthropometr*:ti,ab OR adiposity:ti,ab OR ‘calf circumference’:ti,ab OR ‘failure to thrive’:ti,ab OR ‘skin fold*’:ti,ab OR skinfold*:ti,ab OR ‘normal weight’:ti,ab OR ‘weight for age’:ti,ab OR ‘height for age’:ti,ab OR ‘recumbent length’:ti,ab OR ‘length for age’:ti,ab OR ‘weight for length’:ti,ab OR ‘body composition’/mj OR ‘waist circumference’/de OR ‘body height’/de OR ‘growth chart’/de OR ‘body weight’/de OR ‘anthropometry’/exp OR ‘body growth’/de OR ‘growth’/de OR ‘overnutrition’/de OR ‘failure to thrive’/exp OR ‘weight for age’/exp OR ‘height for age’/exp OR ‘length for age’/exp OR ‘rapid infant weight gain’:ti,ab
  - #3 - ‘dietary supplement’/exp OR supplement*:ti,ab OR drops:ti,ab OR multivitamin*:ti,ab OR ‘multivitamin’/exp
  - #4 - #1 AND #2 AND #3
  - #5 - #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

#### Cumulative Index of Nursing and Allied Health Literature (CINAHL Plus)

- Provider: EBSCOhost
- Date(s) Searched: January 6, 2020
- Date range searched: January 1, 2000- January 6, 2020
- Search terms:
  - #1 - (MH “Iron”) OR (MH “iron compounds) OR iron OR ferrous OR ferric
  - #2 - (MH “body weights and measures”) OR (MH “body weight”) OR obesity OR obese OR overweight OR “body mass index” OR BMI OR underweight OR wasting OR “healthy weight” OR (MH “body composition”) OR “body composition” OR “body fat” OR “fat mass” OR “fat free mass” OR stunting OR stunted OR (MH “growth charts”) OR “growth chart*” OR “waist circumference” OR “head circumference” OR “arm circumference” OR “thigh circumference” OR “neck circumference” OR (MH “anthropometry”) OR (MH “Growth”) OR (MH “overnutrition”) OR (MH “failure to thrive”) OR anthropometr* OR adiposity OR “calf circumference” OR “failure to thrive” OR “skin fold*” OR “skin fold*” OR “normal weight” OR “healthy weight” OR “weight for height” OR “stature for age” OR “weight for age” OR “height for age” OR “recumbent length” OR “length for age” OR “weight for length” OR “rapid infant weight gain”
  - #3 - (MH “dietary supplements”) OR supplement* OR drops OR multivitamin*
  - #4 - #1 AND #2 AND #3
  - #5 - #4 NOT (MH “Literature Review” OR MH “Meta Analysis” OR MH “Systematic Review” OR MH “News” OR MH “Retracted Publication” OR MH “Retraction of Publication )

Filters: Published Date: 20000101 to 20200106, English, Human

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 8 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they met criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

The electronic search of PubMed, Embase, Cochrane, and CINAHL retrieved 3363 records. After the removal of duplicates 2069 titles were screened. Of these, 1647 were excluded and 422 moved on to abstract screening. Of the 422 abstracts screened, 391 were excluded and 31 moved on to full-text sreening. Of the 31 full-text articles, 23 were excluded and 8 were included in the systematic review. Two additional articles were included from a manual search, resulting in 10 articles total.

### Excluded articles

The table below lists the articles excluded after full-text screening. At least one reason for exclusion is provided for each article, which may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 8 Articles excluded after full text screening with rationale for exclusion

| Full texts screened | Rationale for exclusion
1 | Abdelrazik, N.,Al-Haggar, M.,Al-Marsafawy, H.,Abdel-Hadi, H.,Al-Baz, R.,Mostafa, A. H. (2007). Impact of long-term oral iron supplementation in breast-fed infants Indian J Pediatr, 74(8), 739–45 17785896 17785896 | Intervention/exposure vs comparator, Country
2 | Allen, L. H.,Rosado, J. L.,Casterline, J. E.,Lopez, P.,Munoz, E.,Garcia, O. P.,Martinez, H. (2000). Lack of hemoglobin response to iron supplementation in anemic mexican preschoolers with multiple micronutrient deficiencies Am J Clin Nutr, 71(6), 1485–94 10837289 | Outcome, Participant age
3 | Allen, L.,Shrimpton, R. (2005). The international research on infant supplementation study: Implications for programs and further research Journal of Nutrition, 135(3), 666S–669S | Study design
4 | Altucher, K.,Rasmussen, K. M.,Barden, E. M.,Habicht, J. (2005). Predictors of improvement in hemoglobin concentration among toddlers enrolled in the Massachusetts WIC program Journal of the American Dietetic Association, 105(5), 709–715 15883545 | Intervention/exposure vs comparator
5 | Brown, K. H.,De Romaña, D. L.,Arsenault, J. E.,Peerson, J. M.,Penny, M. E. (2007). Comparison of the effects of zinc delivered in a fortified food or a liquid supplement on the growth, morbidity, and plasma zinc concentrations of young Peruvian children American Journal of Clinical Nutrition, 85(2), 538–547 | Intervention/exposure vs comparator
6 | Cotta, R. M. M.,Azeredo, C. M.,da Silva, L. S.,Franceschini, S. C. C.,Sant’Ana, L. F. R.,Ribeiro, R. C. L. (2011). Implementation and impact of the National Iron Supplementation Program in the city of Viçosa, State of Minas Gerais Ciencia e Saude Coletiva, 16(10), 4011–4022 22031130 | Language of publication
7 | Friel, J. K. (2010). Some but not all breast-fed infants benefit from iron supplementation FASEB journal, 24 | Publication status
8 | Gahagan, S.,Yu, S.,Kaciroti, N.,Castillo, M.,Lozoff, B. (2009). Linear and ponderal growth trajectories in well-nourished, iron-sufficient infants are unimpaired by iron supplementation J Nutr, 139(11), 2106–12 19776186 | Intervention/exposure vs comparator
9 | Gondolf, Ulla Holmboe,Tetens, Inge,Michaelsen, Kim F.,Trolle, Ellen (2013). Iron supplementation is positively associated with increased serum ferritin levels in 9-month-old Danish infants British Journal of Nutrition, 109(1), 103–110 | Study design, Intervention/exposure vs comparator
10 | Jabbari, Hossein,Bakhshian, Fariba,Asgari, Mohammad,Sattari, Mohammadreza,Naghavi-Behzad, Mohammad,Mashayekhi, Simin Ozar (2013). Antenatal Micronutrient Supplementation Relationship with Children’s Weight and Height from Birth up to the Age of 18 Months Iranian Journal of Public Health, 42(6), 626–634 23967431 | Participant age
11 | Lopez de Romana, G.,Cusirramos, S.,Lopez de Romana, D.,Gross, R. (2005). Efficacy of multiple micronutrient supplementation for improving anemia, micronutrient status, growth, and morbidity of Peruvian infants J Nutr, 135(3), 646s–652s 15735109 | Intervention/exposure vs comparator
12 | Medeiros, D. A.,Hadler, M. C.,Sugai, A.,Torres, V. M. (2015). The effect of folic acid supplementation with ferrous sulfate on the linear and ponderal growth of children aged 6-24 months: a randomized controlled trial Eur J Clin Nutr, 69(2), 198–204 25335446 | Uncontrolled before after studies
13 | Pongcharoen, T.,Ramakrishnan, U.,DiGirolamo, A. M.,Winichagoon, P.,Flores, R.,Singkhornard, J.,Martorell, R. (2012). Influence of prenatal and postnatal growth on intellectual functioning in school-aged children Arch Pediatr Adolesc Med, 166(5), 411–6 22566539 | Intervention/exposure vs comparator, Outcome
14 | Ramakrishnan, U.,Neufeld, L. M.,Flores, R.,Rivera, J.,Martorell, R. (2009). Multiple micronutrient supplementation during early childhood increases child size at 2 y of age only among high compliers Am J Clin Nutr, 89(4), 1125–31 19225121 | Intervention/exposure vs comparator
15 | Reid, B. M.,Doom, J. R.,Argote, R. B.,Correa-Burrows, P.,Lozoff, B.,Blanco, E.,Gahagan, S. (2019). Pathways to inflammation in adolescence through early adversity, childhood depressive symptoms, and body mass index: A prospective longitudinal study of Chilean infants Brain Behav Immun | Intervention/exposure vs comparator
16 | Richard, S. A.,Zavaleta, N.,Caulfield, L. E.,Black, R. E.,Witzig, R. S.,Shankar, A. H. (2006). Zinc and iron supplementation and malaria, diarrhea, and respiratory infections in children in the Peruvian Amazon Am J Trop Med Hyg, 75(1), 126–32 16837718 | Participant age
17 | Rosado, J. L.,González, K. E.,Caamaño, M. D. C.,García, O. P.,Preciado, R.,Odio, M. (2010). Efficacy of different strategies to treat anemia in children: A randomized clinical trial Nutrition Journal, 9(1) | Participant health
18 | Samadpour, K.,Long, K. Z.,Hayatbakhsh, R.,Marks, G. C. (2011). Randomised comparison of the effects of Sprinkles and Foodlets with the currently recommended supplement (Drops) on micronutrient status and growth in Iranian children Eur J Clin Nutr, 65(12), 1287–94 21750564 | Intervention/exposure vs comparator
19 | Sant’Ana, Lfdr,Cruz, Acrfd,Franceschini, Sdcc,Costa, N. M. B. (2006). Effect of a multi-mixture in the nutritional status of preschool children regarding iron Revista de nutricao, 19(4), 445–454 | Language of publication, Participant age
20 | Wasantwisut, E.,Winichagoon, P.,Chitchumroonchokchai, C.,Yamborisut, U.,Boonpraderm, A.,Pongcharoen, T.,Sranacharoenpong, K.,Russameesopaphorn, W. (2006). Iron and zinc supplementation improved iron and zinc status, but not physical growth, of apparently healthy, breast-fed infants in rural communities of northeast Thailand J Nutr, 136(9), 2405–11 16920862 | Country
21 | Yalcin, S. S.,Yurdakok, K.,Acikgoz, D.,Ozmert, E. (2000). Short-term developmental outcome of iron prophylaxis in infants Pediatr Int, 42(6), 625–30 11192518 | Country
22 | Yang, Q.,Yin, S.,Zhao, X.,An, J. (2004). Effect of daily or once weekly iron supplementation on growth and iron status of preschool children Wei sheng yan jiu [Journal of hygiene research], 33(2), 205–207 | Language of publication
23 | Yurdakok, K.,Temiz, F.,Yalcin, S. S.,Gumruk, F. (2004). Efficacy of daily and weekly iron supplementation on iron status in exclusively breast-fed infants J Pediatr Hematol Oncol, 26(5), 284–8 15111779 | Country

v Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

vi The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).

vii U.S. Food and Drug Administration. Version 19 December 2013. Internet: https://www.fda.gov/Food/GuidanceRegulation/GuidanceDocumentsRegulatoryInformation/InfantFormula/ucm136118.htm#manufacture (accessed March 23, 2018).

viii Food and Agriculture Organization of the United Nations. World Health Organization. Codex Alimentarius. International Food Standards. Standard for infant formula and formulas for special medical purposes intended for infants. Codex Stan 72-1981. 2007.