# WHAT IS THE RELATIONSHIP BETWEEN IRON FROM SUPPLEMENTS CONSUMED DURING INFANCY AND TODDLERHOOD AND GROWTH, SIZE, AND BODY COMPOSITION?

## PLAIN LANGUAGE SUMMARY

### What is the question?

- The question is: What is the relationship between iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition?

### What is the answer to the question?

- Moderate evidence indicates that human milk-fed infants who are supplemented with iron do not have greater growth, and may have slower growth, than human milk-fed infants not supplemented with iron.
- Insufficient evidence is available to determine the relationship between iron from supplements consumed during infancy and body composition during infancy.
- Insufficient evidence is available to determine the relationship between iron from supplements consumed during infancy and growth, size, and body composition beyond age 12 months.
- Insufficient evidence is available to determine the relationship between iron from supplements consumed after age 12 months and growth, size, and body composition.

### Why was this question asked?

- This important public health question was identified by the U.S. Departments of Agriculture (USDA) and Health and Human Services (HHS) to be examined by the 2020 Dietary Guidelines Advisory Committee.

### How was this question answered?

- The 2020 Dietary Guidelines Advisory Committee, Birth to 24 Months Subcommittee, conducted a systematic review to answer this question with support from the Nutrition Evidence Systematic Review (NESR) team.

### What is the population of interest?

- Iron supplementation was examined in healthy infants and toddlers (birth to 24 months) with outcomes measured at any age.

### What evidence was found?

- This review includes 10 articles.
- The articles examined infants and toddlers who consumed iron from supplements. Most studies compared infants who consumed iron from supplements with infants who did not consume iron from supplements. Fewer studies compared infants who consumed iron from supplements with infants who consumed different dosages of iron from supplements or iron from fortified foods.
- The outcomes of interest were growth, size, and body composition at any age, however the articles only examined growth and size and almost all of the outcomes were measured during infancy.
- The evidence indicated that infants fed human milk who are supplemented with iron do not have greater growth, and may have slower growth, than infants not supplemented with iron.
- There are limitations in the evidence as follows:
  ○ There were not a lot of articles, and some of the articles studied groups of infants and toddlers that may have been too small to detect a relationship between iron supplementation and growth or size.
  ○ The studies differed from one another in some important ways, such as the timing of iron supplementation, infants’ consumption of iron-fortified infant formula or iron-rich foods, and the study populations examined, which may have had differences in risk.

### How up-to-date is this systematic review?

- This review searched for studies from January 2000 to January 2020

## FULL REVIEW

### Systematic review question

What is the relationship between iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition?

### Conclusion statements and grades

Moderate evidence indicates that human milk-fed infants who are supplemented with iron do not have greater growth, and may have slower growth, than human milk-fed infants not supplemented with iron. (Grade: Moderate)

Insufficient evidence is available to determine the relationship between iron from supplements consumed during infancy and body composition during infancy. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between iron from supplements consumed during infancy and growth, size, and body composition beyond age 12 months. (Grade: Grade not assignable)

Insufficient evidence is available to determine the relationship between iron from supplements consumed after age 12 months and growth, size, and body composition. (Grade: Grade not assignable)

### Summary of the evidence

- Ten articles met the inclusion criteria for this systematic review,^1–10^ which presented evidence from 8 randomized controlled trials, 1 non-randomized controlled trial, and 1 study that did not clearly describe its prospective study design.
- The intervention or exposure of interest was iron from supplements consumed during infancy and toddlerhood. Dietary supplements are products that contain one or more dietary ingredients (in this case, iron) intended to be taken by mouth to supplement the diet.^ii^ Nine studies examined iron supplementation during infancy, and only 1 study examined iron supplementation during toddlerhood.
- The comparators of interest were different dosages of iron from supplements and iron from fortified foods.
- The outcomes of interest were measures of growth, size, and body composition at any age. However, no articles were identified that examined outcomes beyond 24 months. The articles presented evidence about growth (i.e., change in size between birth or baseline and follow-up) and size (i.e., attained size at follow-up). However, no articles presented evidence about body composition (e.g., percent fat mass, skinfold thickness).
- Moderate evidence, from 5 studies that compared iron from supplements with no iron from supplements, indicated that human milk-fed infants who are supplemented with iron do not have greater growth, and may have slower growth, than human milk-fed infants not supplemented with iron. Inconsistencies in the evidence may be explained by differences in the risk of iron deficiency between the populations studied, differences in participants’ consumption of iron-fortified formula or iron-rich foods, and differences in the timing of iron supplementation. This heterogeneity, the small number of studies, and the small sample sizes, were the primary factors limiting the ability to draw stronger conclusions.
- Evidence available from 3 studies was insufficient to determine whether a relationship exists between iron from supplements, compared with a different dosage or duration of iron from supplements, and growth or size, because the studies used heterogeneous interventions that could not be compared.
- Evidence available from 2 studies was insufficient to determine whether a relationship exists between iron from supplements, compared with iron from fortified foods, and growth or size, because the studies used heterogeneous interventions that could not be compared.

### Description of the evidence

This systematic review examines available evidence about the relationship between iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition throughout the lifespan.

Ten articles, published between 2002 and 2016, met the inclusion criteria, including 8 randomized controlled trials,^3–10^ 1 non-randomized controlled trial,^1^ and 1 study that did not clearly describe its prospective study design^2^ (Table 3).

#### Population

Nine studies examined infant participants, and most of these studies focused on infants fed human milk. One study examined toddlers.^1^ Study participants were from the United States (U.S.),^9,10^ Brazil,^1,3^ Canada,^5^ China,^7^ Italy,^2^ Sweden,^4,8^ and Turkey.^6^ The U.S. samples were predominantly or entirely White, and no other studies reported race or ethnicity.

##### Eligibility criteria related to anemia and/or iron status

Seven studies applied eligibility criteria related to anemia and/or iron status at enrollment:

- Hemoglobin ≥90 g/L,^4^ and ≥110 g/L^1,3^
- Cord blood serum ferritin ≥35 μg/L^7^
- Hemoglobin ≥100 g/L and serum ferritin ≥12 μg/L^8^
- No iron deficiency^9^ or iron-deficiency anemia^6^

Three studies did not report eligibility criteria related to anemia or iron status.^2,5,10^

##### Baseline iron status

Eight studies reported mean hemoglobin at baseline:

- Azeredo et al^1^: 124 g/L at 6-18 months
- da Silva et al^3^: 118-122 g/L at 5-7 months, depending on the group
- Dewey et al^4^: 117-121 g/L at 4 months, depending on the group
- Friel et al^5^: 124-126 g/L at 1 month, depending on the group
- Hacihamdioglu et al^6^: 112-116 g/L at 4 months, depending on the group; this study also reported other iron status indicators at baseline: hematocrit 32.2-35.3%, mean corpuscular volume 77.9-80.9 fL, mean corpuscular hemoglobin concentration 32.7-33.2 g/dL, red cell distribution width 12.2-13.1%, ferritin 82.2-83.5 μg/L
- Szymlek-Gay et al^8^: 108-113 g/L at 6 months, depending on the group
- Ziegler et al^9^: 114-115 g/L at 4 months, depending on the group; this study also reported other iron status indicators at baseline: ferritin 89-134 μg/L, transferrin receptor 6.27-6.37 mg/L, red cell distribution width 12.3-12.4%, mean corpuscular volume 81-82 fL
- Ziegler et al^10^: 127-132 g/L at 1 month, depending on the group; this study also reported other iron status indicators at baseline: plasma ferritin 123-152 μg/L, serum transferrin receptor 5.65-5.74 mg/L, red cell distribution width 12.2-12.6%, mean corpuscular volume 81-82 fL

Two studies did not report iron status at baseline.^2,7^ However, Lozoff et al^7^ reported iron status at birth (6 weeks prior to baseline):

- Lozoff et al^7^: hemoglobin 149-154 g/L depending on the group, 41.0-43.5% iron deficiency (defined as cord blood serum ferritin <75 μg/L or zinc protoporphyrin/heme >118 μmol/mol heme, which is the U.S. 90^th^ percentile), mean corpuscular volume 102-103 fL, serum ferritin 113-116 μg/L, zinc protoporphyrin/heme 94.3-97.8 μmol/mol heme, serum transferrin receptor 29.5-31.0 nmol/L, body iron 7.31-7.42 mg/kg

#### Interventions and comparators

[underlined: Intervention]: The intervention was iron from supplements consumed during infancy and toddlerhood. The form, dosage, and intervention periods are described below.

Form:

- Eight studies provided iron in the form of ferrous sulfate^1,3–6,8–10^
- Lozoff et al^7^ provided iron proteinsuccinylate
- Capozzi et al^2^ did not report the form of iron

Dosage:

- The most common dosage of iron provided by the supplements was 1 mg/d per kg of infant body weight (i.e., 1 mg/kg/d)^1–4,7^
- One study provided a different dosage dependent on infant body weight: 2 mg/kg/d^3^
- Five studies provided dosages not dependent on infant body weight:
  ○ 6.6 mg/d^8^
  ○ 7 mg/d^10^
  ○ 7.5 mg/d^5,9^
  ○ 10 mg/d^6^

Intervention period:

The intervention period began as early as 1 month of age and as late as 6 to 18 months of age, and lasted between 1.5 and 7.5 months in duration (Table 1).

Table 1 Summary of the intervention periods, according to baseline age of infants and the duration of iron supplementation

Intervention periods, from youngest to oldest baseline age | Intervention periods, from shortest to longest duration
1 to 5.5-6 months ^5^ ^,^ ^10^; 6 weeks to 9 months ^7^; 4 to 6 months ^6^; 4 to 9 months ^2^ ^,^ ^4^ ^,^ ^9^; 5-7 to 9-11 months ^3^; 6 to 7.5 months ^8^; 6 to 9 months ^4^; 6-18 months to 12-24 months ^1^ | 1.5 months; (6 to 7.5 months^8^); 2 months; (4 to 6 months^6^); 3 months; (6 to 9 months^4^); 4 months; (5-7 to 9-11 months^3^); 4.5 months; (1 to 5.5 months^10^); 5 months; (1 to 6 months^5^, 4 to 9 months^2,4,9^); 6 months; (6-18 to 12-24 months^1^); 7.5 months; (6 weeks to 9 months^7^)

##### Comparator

Study comparators can be categorized into 3 groups:

1. No iron: 3 studies compared infants given iron supplements with infants in a control group given no iron,^2,6,9^ and 4 studies compared infants given iron supplements with infants given a placebo.^4,5,7,10^
2. Different amount of iron from supplements: 3 studies compared infants given iron supplements with infants given a different dosage or duration of iron supplements.^1,3,4^
  Different dosage:
  ○ 25 mg/wk (compared to the intervention dosages of 1 mg/kg/d^1,3^ and 2 mg/kg/d^3^)
  ○ 2 mg/kg/d (compared to the intervention dosage of 1 mg/kg/d^3^)
  Different duration:
  ○ 1 mg/kg/d from 6 to 9 months compared to 1 mg/kg/d from 4 to 9 months^4^
3. Iron from fortified foods: 3 studies compared infants given iron from supplements with infants given iron from fortified foods.^2,8,9^
  ○ Capozzi et al^2^ had comparison groups that were (a) fed human milk exclusively for 5-6 months and weaned with iron-fortified food, and (b) fed iron-fortified infant formula for 5-6 months and weaned with iron-fortified food [compared to an intervention group fed human milk exclusively for 5-6 months and given 1 mg/kg/d iron supplement from 4 to 9 months (complementary foods for the intervention group were not described)].
  ○ Szymlek-Gay et al^8^ had comparison groups fed (a) high-iron infant formula (dosage of 6.6 mg/d), and (b) low-iron infant formula (dosage of 1.3 mg/d) (compared to an intervention group fed no-added-iron formula and iron supplementation at a dosage of 6.6 mg/d).
  ○ Ziegler et al^9^ had a comparison group fed iron-fortified cereal at an estimated dosage of 7 mg/d (compared to the intervention group given iron supplements at a dosage of 7.5 mg/d).

#### Outcomes

Six studies reported measures of change in size from birth or baseline to follow-up, and 7 studies reported measures of attained size at follow-up (Table 2). Measures of attained size in the studies by Hacihamdioglu et al,^6^ Ziegler et al,^10^ and Lozoff et al^7^ should be interpreted with caution. In these 3 studies, there were baseline differences in size between groups and the differences were not controlled for in the analyses. Measures of attained size in the in the study by Cappozi et al^2^ should also be interpreted with caution, because the authors did not report any assessments of differences in baseline size between groups.

Table 2 Summary of the outcome measures, according to measures of change in size from birth or baseline to follow-up and measures of attained size at follow-up

Intervention periods, from shortest to longest | Outcome measures of change in size from birth or baseline to follow-up | Outcome measures of attained size at follow-up
1.5 months; From 6 to 7.5 months^8^ | 1.5-month change in:; weight; weight-for-age z-score; length; length-for-age z-score; head circumference; head circumference-for-age z-score; knee-heel length; (from 6 to 7.5 months) | .
2 months; From 4 to 6 months^6^ | . | At 6 months:; Weight; height^*^; head circumference
3 months; From 6 to 9 months^4^ | 2-month change in:; weight; length; head circumference; (from 4 to 6 months); 3-month change in:; weight; length; head circumference; (from 6 to 9 months); 5-month change in:; weight; length; head circumference; (from 4 to 9 months)
4 months; From 5-7 to 9-11 months^3^ | 4-month change in:; weight; weight-for-age z-score; length; length-for-age z-score; weight-for-length z-score; (from 5-7 to 9-11 months) | .
4.5 months; From 1 to 5.5 months^10^ | 4.5-month change in:; weight; length; (from 1 to 5.5 months) | At 5.5 months:; weight; length
5 months; From 1 to 6 months^5^; From 4 to 9 months^2,4,9^ | 2-month change in:; weight; length; head circumference; [from 4 to 6 months^4^]; 3-month change in:; weight; length; head circumference; [from 6 to 9 months^4^]; 5-month change in:; weight; length; head circumference; [from 4 to 9 months^4,9^] | At 3.5, 6, and 12 months:; weight; length; head circumference^5^; At 6, 12, 18, and 24 months:; weight; length^2^; At 9 months:; weight; length^9^
6 months; From 6-18 to 12-24 months^1^ | . | At 12-24 months^:^; weight; weight-for-age z-score; height^*^; height-for-age z-score^*^; weight-for-height z-score^*^; BMI z-score
7.5 months; From 6 weeks to 9 months^7^ | 9-month change in:; weight; length; (from birth to 9 months) | At 9 months:; weight-for-age z-score; height-for-age z-score^*^; weight-for-height z-score^*^; head circumference z-score

* The authors used the term “height” however it may be “length” given the age of the participants

### Synthesis and assessment^iii^ of the evidence

This evidence synthesis will focus on analyses that report growth (i.e., change in size from birth or baseline to follow-up) or attained size if the study groups were similar in size at baseline or the authors adjusted for size at baseline. Two studies reported measures of attained size among infants who were significantly different in size at baseline for at least some of their analyses,^6,10^ and 1 study did not report whether infants differed in size at baseline.^2^ The synthesis and assessment of the remaining evidence follows.

#### Infants given iron from supplements compared with infants not given iron from supplements or infants given a placebo

Consistency: The evidence had moderate consistency.

Four studies examined differences in growth between infants given iron from supplements and infants given either no iron from supplements or a placebo. Three of the 4 studies reported significant differences in growth between the comparison groups, although the growth outcomes that differed between groups varied between studies:

- Ziegler et al^9^ compared infants given 7.5 mg/d of iron from supplements from 4 to 9 months of age with infants in a control group who were given neither a supplement nor a placebo. Infants in the iron supplement group had significantly smaller gains in weight and length from 4 to 9 months than infants in the control group.
- Dewey et al^4^ compared Swedish infants given 1 mg/kg/d of iron for 5 months (i.e., from 4 to 9 months of age) and for 3 months (i.e., placebo from 4 to 6 months of age and then 1 mg/kg/d of iron from 6 to 9 months of age) with infants given a placebo from 4 to 9 months of age. Infants supplemented from 4 to 9 months of age had a significantly lower change in length from 6 to 9 months than infants given a placebo from 4 to 9 months; however, change in length over the entire 4- to 9-month period was not significantly different between groups. Infants supplemented from 4 to 9 months also had a significantly lower change in head circumference from 4 to 6 months and across the whole 4- to 9-month period than infants in the placebo group. There were no significant differences in weight gain between groups. There were also no significant differences in any measures of growth between infants given a placebo from 4 to 6 months preceding iron supplementation from 6 to 9 months compared with infants given a placebo from 4 to 9 months.
- Ziegler et al^10^ compared infants given 7 mg/d of iron for 4.5 months with infants given a placebo. Among females, those given iron gained significantly less weight from 1 to 5.5 months than those given placebo. Among males, weight gain did not differ between intervention groups. There were no significant group differences in length gain in either females or males.
- In contrast to the 3 studies above, Lozoff et al^7^ reported no significant differences in growth between comparison groups. The study compared infants given about 1 mg/kg/d of iron from 6 weeks to 9 months of age with infants given a placebo and stratified the analyses based on maternal prenatal iron supplementation. There were no significant differences in weight or length gain from birth to 9 months.

Four studies examined differences in attained size among infants who were similar in size at baseline. Three of these 4 studies also examined growth outcomes, as described above. One of the 4 studies reported significant differences between infants given iron from supplements and infants given either no iron from supplements or a placebo:

- Consistent with the significant findings for growth described above, Ziegler et al^10^ reported that among females, those given 7 mg/d of iron from 1 to 5.5 months of age weighed less at 5.5 months than those given a placebo, even though groups were similar at baseline. There was no significant group difference in length at 5.5 months among females. (Findings in males are not discussed here because male infants in the supplementation group were smaller at birth and baseline than male infants in the placebo group.)
- The remaining 3 studies found no significant differences in attained size.
  ○ Consistent with the nonsignificant findings for growth described above, Lozoff et al^7^ reported no significant differences in weight-for-age z-score, height-for-age z-score, weight-for-height z-score, or head circumference z-score at 9 months between comparison groups.
  ○ Inconsistent with the significant findings for growth described above, Ziegler et al^9^ found no significant differences in weight or length at 9 months, reported by sex, between infants given 7.5 mg/d of iron from 4 to 9 months, compared with no iron supplementation and no placebo. This inconsistency may be due to the smaller analysis groups; the significant findings for growth, above, included the full sample whereas the nonsignificant findings for size were stratified into smaller groups by sex.
  ○ Friel et al^5^ compared infants given 7.5 mg/d of iron from 1 to 6 months of age with infants given a placebo, and found no significant differences in weight, length, or head circumference measured at 3.5, 6, and 12 months.

In summary, of the 5 studies described above, 3 reported significant differences between intervention groups in one or more growth outcomes (all in the same direction, i.e., slower growth among infants given iron supplements) and 2 did not. There are several possible explanations for this inconsistency.

First, the study populations differed in several characteristics that may be related to risk of iron deficiency and therefore the potential impact of iron supplements on growth. Four studies were conducted among populations with medium to high average socio-economic or educational status,^4,5,9,10^ whereas the study by Lozoff et al^7^ was conducted in rural China and only about one-third of mothers had a high-school education or greater (see Generalizability). Risk of iron deficiency appeared to be greater in the study by Lozoff et al,^7^ based on average hemoglobin and serum ferritin concentrations at 9 months of age in the control or placebo groups. For hemoglobin, those values were 111 g/L in the study by Lozoff et al^7^ compared to 116, 115 and 114 g/L in the studies by Ziegler et al,^9^ Ziegler et al,^10^ and Dewey et al,^iv^ respectively. For serum ferritin those values were 11 μg/L in the study by Lozoff et al. compared to 28, 43 and 23 μg/L in the studies by Ziegler et al,^9^ Ziegler et al,^10^ and Dewey et al,^iv^ respectively. For the study by Friel et al,^5^ this information is not available, but the investigators reported that average serum ferritin in the placebo group was 27 μg/L at 6 months and 14 μg/L at 12 months.

Second, the studies differed in the extent to which the infants were supplemented with iron-fortified infant formula or iron-rich foods, which may have obscured effects of iron supplementation on growth. Although all studies enrolled infants who were initially breastfed, 3 reported that a substantial proportion of infants ceased breastfeeding and/or were supplemented with infant formula,^5,9,10^ whereas Dewey et al^4^ enrolled mothers who intended to exclusively breastfeed until 6 months (except for small “tastes” of low-iron foods) and to continue breastfeeding until at least 9 months; in the study by Lozoff et al,^7^ investigators reported that more than 80% of infants were still breastfeeding at 9 months, and >50% received breast milk as the sole milk source.

Lastly, the timing of iron supplementation differed among studies. Of the 3 studies that began iron supplementation at 1 month or 6 weeks, 2 did not report significant differences in growth between intervention groups,^5,7^ and the third reported significant group differences in growth among females but not among male infants.^10^ The two studies that began iron supplementation at about 4 months both showed significant group differences in growth.^4,9^

Precision: The evidence had limited precision.

There was a small number of studies overall. Only Lozoff et al^7^ reported a power analysis related to growth outcomes, so it is unclear whether all studies had sufficient statistical power for all of the analyses of interest.

Directness: The evidence had moderate directness.

Three of the studies reported objectives that included assessing the effect of iron supplementation on infant growth^4,5,7^ and 2 studies did not.^9,10^

Generalizability: The evidence had moderate generalizability.

Four studies were likely to be generalizable to healthy infants from the U.S.^4,5,9,10^ whereas 1 study^7^ had limited generalizability to healthy infants from the U.S. There is limited generalizability to iron supplementation and its effect on growth and size outside of infancy.

Risk of bias: There is a moderate likelihood that the design and conduct of the studies have prevented or minimized bias.

The evidence is from randomized controlled trials. Further, this evidence synthesis does not examine differences in attained size between randomization groups that differed in size at baseline (i.e., with a failure of randomization). There were some risks of bias, which differed between studies (Table 4).

Publication bias: In addition to the graded elements of the assessment of the evidence, above, it is important to give consideration to publication bias. There is not a strong indication of publication bias. Although only 5 included studies examined infants given iron from supplements compared with infants not given iron from supplements or infants given a placebo, they presented evidence with some variability. As described above, 3 of the 5 studies reported significant differences between intervention groups in one or more growth outcomes although the growth outcomes that differed between groups varied between studies.

#### Infants given iron from supplements compared with infants given a different dosage or duration of iron from supplements

Only 3 studies examined infants given iron from supplements compared with infants give a different dosage or duration of iron from supplements. The consistency and precision of the evidence cannot be adequately assessed due to the heterogeneity of the interventions. The risk of bias of the 3 studies is summarized in (Table 4,Table 5).

Two studies examined growth in infants given different dosages or durations of iron from supplements. One reported a significant difference in head circumference growth between infants given iron supplements for different durations, and the second reported no significant differences in growth between infants given different dosages of iron from supplements:

- Dewey et al^4^ compared Swedish infants given iron supplements at a dosage of 1 mg/kg/d for 5 compared to 3 months. Infants supplemented from 4 to 9 months of age had a significantly lower change in head circumference from 4 to 9 months of age than infants given a placebo from 4 to 6 months followed by supplementation from 6 to 9 months of age. Weight and length gain did not differ significantly between these two groups.
- da Silva et al^3^ found no significant differences in growth from 5-7 to 9-11 months of age between infants given: (a) a daily dosage of 1 mg/kg vs a daily dosage of 2 mg/kg, (b) a daily dosage of 1 mg/kg vs a weekly dosage of 25 mg, or (c) a daily dosage of 2 mg/kg vs a weekly dosage of 25 mg from 5-7 to 9-11 months of age.

One study examined attained size in infants who were similar in size at baseline, and did not find any significant differences between infants given different dosages of iron from supplements:

- Azeredo et al^1^ found no significant differences in attained size at 12-24 months of age between children given a daily dosage of 1 mg/kg and children given a weekly dosage of 25 mg from 6-18 to 12-24 months of age.

#### Infants given iron from supplements compared with infants given iron from fortified foods

Only 2 studies examined infants given iron from supplements compared with infants given iron from fortified foods. The consistency and precision of the evidence cannot be adequately assessed due to the heterogeneity of the interventions. The risk of bias of the 2 studies is summarized in Table 4.

Both studies examined growth or attained size in infants given iron from supplements compared with infants given iron from fortified foods. One of the 2 studies reported a significant difference in growth:

- Szymlek-Gay et al^8^ found that infants given 6.6 mg/d of iron as a supplement from 6 to 7.5 months of age had a significantly greater change in head circumference during the intervention period than infants given the same amount of iron in a high-iron infant formula. There were no significant differences in other measures of growth (i.e., head circumference-for-age z-score, weight, weight-for-age z-score, length, length-for-age z-score, and knee-heel length). Further, there were no significant differences in any growth measures between infants fed 6.6 mg/d of iron as a supplement and infants fed 1.3 mg/d of iron in a low-iron infant formula.
- Ziegler et al^9^ reported no significant differences in growth (i.e., weight gain and length gain from 4 to 9 months of age, reported by sex) or attained size (weight and length at 9 months of age, reported by sex) between infants given 7.5 mg/d of iron from supplements and infants who consumed an estimated 7 mg/d of iron from iron-fortified cereal from 4 to 9 months of age.

#### Conclusion

Given this synthesis and assessment of the evidence, we conclude that:

- Moderate evidence indicates that human milk-fed infants who are supplemented with iron do not have greater growth, and may have slower growth, than human milk-fed infants not supplemented with iron.
- Insufficient evidence is available to determine the relationship between iron from supplements consumed during infancy and body composition during infancy.
- Insufficient evidence is available to determine the relationship between iron from supplements consumed during infancy and growth, size, and body composition beyond 12 months of age.
- Insufficient evidence is available to determine the relationship between iron from supplements consumed after 12 months of age and growth, size, and body composition.

Table 3 Evidence examining the relationship between iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition^*^

Article; Study design; Country | Iron from supplements intervention vs comparator^†^ | Growth, size, and body composition outcome^‡^ | Significant findings | Nonsignificant findings
Iron from supplement compared with no iron or placebo
Capozzi 2011 ^2^; PC or NRCT or RCT^§^; Italy | EBF 5-6 mo and weaned with non-iron fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | Weight (mean ± SD, kg)
Capozzi 2011 ^2^; PC or NRCT or RCT^§^; Italy | EBF 5-6 mo and weaned with non-iron fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | In males (N=15, 14)
Capozzi 2011 ^2^; PC or NRCT or RCT^§^; Italy | EBF 5-6 mo and weaned with non-iron fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | at 6 mo | 7.2 ± 0.24 vs 7.2 ± 0.8; p<0.05 | .
| | at 12 mo | . | 9.2 ± 0.9 vs 9.4 ± 1.5; NS
| | at 18 mo | . | 11.8 ± 1.2 vs 12.6 ± 0.9; NS
| | at 24 mo | 11.5 ± 0.9 vs 12.9 ± 2.1; p<0.05 | .
| | In females (N=20, 12)
| | at 6 mo | 6.8 ± 0.21 vs 7.2 ± 0.9; p<0.05 | .
| | at 12 mo | . | 8.9 ± 0.5 vs 9.1 ± 1.1; NS
| | at 18 mo | . | 10.7 ± 1.2 vs 11.9 ± 1.8; NS
| | at 24 mo | 10.9 ± 1.2 vs 12.8 ± 1.1; p<0.05 | .
| | Length (mean ± SD, cm) at 6 mo
| | In males (N=15, 14)
| | at 6 mo | . | 67 ± 1.2 vs 67.1 ± 0.6; NS
| | at 12 mo | 74.5 ± 1.2 vs 73.4 ± 0.7; p<0.05 | .
| | at 18 mo | 81.1 ± 2.1 vs 78.1 ± 1.2; p<0.05 | .
| | at 24 mo | 86.6 ± 1.4 vs 83.5 ± 1.9; p<0.05 | .
| | In females (N=20, 12)
| | at 6 mo | . | 64.6 ± 1.35 vs 63.9 ± 1.3; NS
| | at 12 mo | 72.4 ± 1.3 vs 70 ± 2.1; p<0.05 | .
| | at 18 mo | 78.9 ± 0.9 vs 77.1 ± 0.6; p<0.05 | .
| | at 24 mo | 84.2 ± 2.1 vs 82.1 ± 1.9; p<0.05 | .
Hacihamdioglu 2013 ^6^; RCT; Turkey | Iron supplement from 4 to 6 mo (10 mg/d) vs control (no iron or placebo described) | Weight (mean ± SD, kg) at 6 mo (N=27, 26) | 7.1 ± 0.9 vs 6.6 ± 0.7; p=0.048 | .
| | Height (mean ± SD, cm) at 6 mo (N=27, 26) | 65.9 ± 2.0 vs 67.5 ± 2.3; p=0.012 | .
| | Head circumference (mean ± SD, cm) at 6 mo (N=27, 26) | . | 43.2 ± 1.4 vs 43.9 ± 2.5; NS
Ziegler 2009 ^9^; RCT; US | Iron supplement from 4 to 9 mo (7.5 mg/d) vs control (no iron or placebo provided) | Weight (mean ± SD, g) at 9 mo | .
Ziegler 2009 ^9^; RCT; US | Iron supplement from 4 to 9 mo (7.5 mg/d) vs control (no iron or placebo provided) | In male subsample (N=18, 28) | . | 9114 ± 970 vs 9179 ± 877; NS
| | In female subsample (N=23, 26) | . | 8197 ± 732 vs 8555 ± 772; NS
| | Weight gain (mean ± SD, g/d) from 4 to 9 mo (N=41, 54) | 12.18 (SD NR) vs 13.58 (SD NR); p=0.027 | .
| | In male subsample (N=18, 28) | . | 12.7 ± 2.39 vs 13.9 ± 3.30; NS
| | In female subsample (N=23, 26) | . | 11.6 ± 3.23 vs 13.3 ± 3.39; NS
| | Length (mean ± SD, cm) at 9 mo | .
| | In male subsample (N=18, 28) | . | 72.0 ± 1.92 vs 71.5 ± 1.84; NS
| | In female subsample (N=23, 26) | . | 69.2 ± 1.79 vs 70.1 ± 1.96; NS
| | Length gain (mean ± SD, mm/d) from 4 to 9 mo (N=41, 54) | 0.484 (SD NR) vs 0.519 (SD NR); p=0.011 | .
| | In male subsample (N=18, 28) | . | 0.50 ± 0.071 vs 0.51 ± 0.060; NS
| | In female subsample (N=23, 26) | . | 0.47 ± 0.062 vs 0.52 ± 0.072; NS
Iron from supplement compared to placebo
Dewey 2002 ^4^; RCT; Sweden | Placebo from 4 to 9 mo vs Placebo from 4 to 6 mo and iron supplement from 6 to 9 mo (1 mg/kg/d) | Weight gain (mean ± SE, g)
Dewey 2002 ^4^; RCT; Sweden | Placebo from 4 to 9 mo vs Placebo from 4 to 6 mo and iron supplement from 6 to 9 mo (1 mg/kg/d) | from 4 to 6 mo (N=36, 34) | . | 967 ± 52 vs 860 ± 54; NS
| | from 6 to 9 mo (N=36, 30) | . | 1175 ± 69 vs 1137 ± 75; NS
| | from 4 to 9 mo (N=36, 30) | . | 2134 ± 92 vs 2013 ± 100; NS
| | Length gain (mean ± SE, cm)
| | from 4 to 6 mo (N=36, 34) | . | 3.07 ± 0.15 vs 3.02 ± 0.15; NS
| | from 6 to 9 mo (N=36, 30) | . | 4.68 ± 0.19 vs 4.22 ± 0.21; NS
| | from 4 to 9 mo (N=36, 30) | . | 7.79 ± 0.21 vs 7.14 ± 0.23; NS
| | Change in head circumference (mean ± SE, cm)
| | from 4 to 6 mo (N=36, 34) | . | 1.78 ± 0.06 vs 1.74 ± 0.06; NS
| | from 6 to 9 mo (N=36, 30) | . | 2.11 ± 0.07 vs 2.09 ± 0.07; NS
| | from 4 to 9 mo (N=36, 30) | . | 3.88 ± 0.08 vs 3.84 ± 0.09; NS
| Placebo from 4 to 9 mo vs Iron supplement from 4 to 9 mo (1 mg/kg/d) | Weight gain (mean ± SE, g)
| Placebo from 4 to 9 mo vs Iron supplement from 4 to 9 mo (1 mg/kg/d) | from 4 to 6 mo (N=36, 31) | . | 967 ± 52 vs 880 ± 57; NS
| | from 6 to 9 mo (N=36, 30) | . | 1175 ± 69 vs 1054 ± 75; NS
| | from 4 to 9 mo (N=36, 30) | . | 2134 ± 92 vs 1925 ± 101; NS
| | Length gain (mean ± SE, cm)
| | from 4 to 6 mo (N=36, 31) | . | 3.07 ± 0.15 vs 3.37 ± 0.16; NS
| | from 6 to 9 mo (N=36, 30) | 4.68 ± 0.19 vs 4.00 ± 0.21; p=0.02 | .
| | from 4 to 9 mo (N=36, 30) | . | 7.79 ± 0.21 vs 7.31 ± 0.23; NS
| | Change in head circumference (mean ± SE, cm)
| | from 4 to 6 mo (N=36, 31) | 1.78 ± 0.06 vs 1.57 ± 0.06; p<0.05 | .
| | from 6 to 9 mo (N=36, 30) | . | 2.11 ± 0.07 vs 2.00 ± 0.07; NS
| | from 4 to 9 mo (N=36, 30) | 3.88 ± 0.08 vs 3.56 ± 0.09; p=0.01 | .
Friel 2003 ^5^; RCT; Canada | Iron supplement from 1 to 6 mo (7.5 mg/d) vs placebo from 1 to 6 mo | Weight (mean ± SD, kg)
Friel 2003 ^5^; RCT; Canada | Iron supplement from 1 to 6 mo (7.5 mg/d) vs placebo from 1 to 6 mo | at 3.5 mo (N=32,24) | . | 6.6 ± 0.9 vs 6.8 ± 0.87; NS
| | at 6 mo (N=30,21) | . | 8 ± 1.03 vs 8.1 ± 0.95; NS
| | at 12 mo (N=23,21) | . | 10.3 ± 1.3 vs 10.8 ± 1.36; NS
| | Length (mean ± SD, cm)
| | at 3.5 mo (N=32,24) | . | 63 ± 2.3 vs 63.4 ± 1.7; NS
| | at 6 mo (N=30,21) | . | 68 ± 2.3 vs 68.2 ± 2.3; NS
| | at 12 mo (N=23,21) | . | 75.7 ± 6.9 vs 77 ± 3.6; NS
| | Head circumference (mean ± SD, cm)
| | at 3.5 mo (N=32,24) | . | 42 ± 1.2 vs 42 ± 1.0; NS
| | at 6 mo (N=30,21) | . | 44 ± 1.3 vs 44 ± 1.0; NS
| | at 12 mo (N=23,21) | . | 48 ± 5.9 vs 47.2 ± 1.3; NS
Lozoff 2016 ^7^; RCT; China | Iron supplement from 6 wk to 9 mo (~1 mg/kg/d) vs placebo from 6 wk to 9 mo | WAZ (mean (95% CI)) at 9 mo
Lozoff 2016 ^7^; RCT; China | Iron supplement from 6 wk to 9 mo (~1 mg/kg/d) vs placebo from 6 wk to 9 mo | In subsample that was iron sufficient at birth (N=360, 347) | . | 0.86 (0.75, 0.96) vs 0.95 (0.84, 1.06); p=0.23
| | In subsample whose mothers received prenatal iron (N=327, 316) | . | 0.97 (0.86, 1.08) vs 0.92 (0.81, 1.03); NS
| | In subsample whose mothers received prenatal placebo (N=321, 312) | . | 0.80 (0.69, 0.91) vs 0.89 (0.77, 1.00); NS
| | Weight gain (mean (95% CI), g) from birth to 9 mo
| | In subsample that was iron sufficient at birth (N=360, 347) | . | 6204 (6088, 6321) vs 6335 (6214, 6455); p=0.13
| | In subsample whose mothers received prenatal iron (N=327, 316) | . | 6356 (6235, 6477) vs 6354 (6231, 6477)
| | In subsample whose mothers received prenatal placebo (N=321, 312) | . | 6161 (6039, 6283) vs 6270 (6146, 6395)
| | HAZ (mean (95% CI)) at 9 mo
| | In subsample that was iron sufficient at birth (N=360, 347) | . | 0.25 (0.14, 0.36) vs 0.33 (0.22, 0.43); p=0.32
| | In subsample whose mothers received prenatal iron (N=327, 316) | . | 0.33 (0.22, 0.45) vs 0.30 (0.18, 0.41); NS
| | In subsample whose mothers received prenatal placebo (N=321, 312) | . | 0.24 (0.13, 0.36) vs 0.33 (0.21, 0.45); NS
| | Length gain (mean (95% CI), cm) from birth to 9 mo
| | In subsample that was iron sufficient at birth (N=360, 347) | . | 22.4 (22.1, 22.7) vs 22.4 (22.1, 22.7); p=0.92
| | In subsample whose mothers received prenatal iron (N=327, 316) | . | 22.7 (22.4, 23.0) vs 22.4 (22.1, 22.7); NS
| | In subsample whose mothers received prenatal placebo (N=321, 312) | . | 22.3 (22.1, 22.6) vs 22.4 (22.1, 22.7); NS
| | WHZ (mean (95% CI)) at 9 mo
| | In subsample that was iron sufficient at birth (N=360, 347) | . | 1.03 (0.91, 1.14) vs 1.10 (0.98, 1.22); p=0.38
| | In subsample whose mothers received prenatal iron (N=327, 316) | . | 1.12 (1.00, 1.24) vs 1.07 (0.95, 1.19); NS
| | In subsample whose mothers received prenatal placebo (N=321, 312) | . | 0.96 (0.84, 1.08) vs 1.02 (0.90, 1.14); NS
| | Head circumference z-score (mean (95% CI)) at 9 mo
| | In subsample that was iron sufficient at birth (N=360, 347) | . | 0.06 (20.05, 0.16) vs 0.06 (20.08, 0.19); p=1.00
| | In subsample whose mothers received prenatal iron (N=327, 316) | . | 0.13 (0.01, 0.26) vs 0.04 (20.08, 0.17); NS
| | In subsample whose mothers received prenatal placebo (N=321, 312) | . | 0.01 (20.11, 0.14) vs 0.10 (20.02, 0.23); NS
Ziegler 2009 ^10^; RCT; US | Iron supplement from 1 to 5.5 mo (7mg/d) vs Placebo from 1 to 5.5 mo | Weight (mean %ile) at 5.5 months | 43.6 vs 67.4; p<0.05 | .
| | In males (N=15, 15)
| | (mean %ile) | 41.7 vs 67.1; p<0.05 | .
| | (mean ± SD, g) | 7440 ± 840 vs 8289 ± 960; p<0.05 | .
| | In females (N=16, 17)
| | (mean %ile) | 45.6 vs 67.6; p<0.05 | .
| | (mean ± SD, g) | 6877 ± 661 vs 7581 ± 855; p<0.05 | .
| | Weight gain (mean %ile change) from 1 to 5.5 mo (N=31, 32) | . | −2.1 vs −2.6; NS
| | In males (N=15, 15)
| | (mean %ile change) | . | +1.5 vs −8.3; NS
| | (mean ± SD, g/d) | . | 23.9 ± 3.6 vs 24.2 ± 5.6; NS
| | In females (N=16, 17)
| | (mean %ile change) | . | −5.6 vs +2.5; NS
| | (mean ± SD, g/d) | 19.7 ± 5.1 vs 22.7 ± 4.6; p<0.05 | .
| | Length (mean %ile) at 5.5 months | 44.9 vs 58.6; p<0.05 | .
| | In males (N=15, 15)
| | (mean %ile) | 43.4 vs 62.6; p<0.05 | .
| | (mean ± SD, cm) | 65.5 ± 2.7 vs 67.3 ± 2.1; p<0.05 | .
| | In females (N=16, 17)
| | (mean %ile) | . | 46.3 vs 55.0; NS
| | (mean ± SD, g) | . | 64.2 ± 1.5 vs 64.8 ± 1.6; NS
| | Length gain (mean %ile change) from 1 to 5.5 mo | . | +0.1 vs −1.7; NS
| | In males (N=15, 15)
| | (mean %ile change) | . | +3.7 vs −1.9; NS
| | (mean ± SD, mm/d) | | 0.882 ± 0.098 vs 0.843 ± 0.103; NS
| | In females (N=16, 17)
| | (mean %ile change) | . | −3.2 vs −1.6; NS
| | (mean ± SD, mm/d) | . | 0.786 ± 0.072 vs 0.792 ± 0.061; NS
Iron from supplement compared to different dosage of iron from supplement
Azeredo 2010 ^1^; NRCT; Brazil | Daily iron supplement from 6-18 mo (mean 11.5 mo) to 12-24 mo (1 mg/kg/d) vs weekly iron supplement from 6-18 mo (mean 11.5 mo) to 12-24 mo (25 mg/wk) | Weight (mean ± SD, kg) at 12-24 mo (N=34, 69) | . | 10.46 ± 1.72 vs 10.21 ± 1.91; p=0.516
| | Height (mean ± SD, cm) at 12-24 mo (N=34, 69) | . | 80.44 ± 5.29 vs 79.63 ± 5.02; p=0.452
| | WAZ (mean ± SD) at 12-24 mo (N=34, 69) | . | −0.18 ± 1.167 vs −0.26 ± 1.291; p=0.748
| | HAZ (mean ± SD) at 12-24 mo (N=34, 69) | . | −0.26 ± 1.214 vs −0.35 ± 1.186; p=0.741
| | WHZ (mean ± SD) at 12-24 mo (N=34, 69) | . | −0.15 ± 0.989 vs −0.14 ± 1.275; p=0.993
| | BMIz (mean ± SD) at 12-24 mo (N=34, 69) | . | −0.09 ± 0.996 vs −0.13 ± 1.316; p=0.869
da Silva 2008 ^3^; RCT; Brazil | Iron supplement from ~5-7 mo to ~9-11 mo (1 mg/kg/d) vs Iron supplement from ~5-7 mo to ~9-11 mo (2 mg/kg/d) | Weight change (mean ± SD, kg) from ~5-7 mo to ~9-11 mo (N=51 42) | . | 1.201±0.503 vs 1.267±0.372; NS
| | Length change (mean ± SD, cm) from ~5-7 mo to ~9-11 mo (N=51 42) | . | 5.15±1.14 vs 5.22±1.01; NS
| | WAZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=51 42) | . | 0.015±0.487 vs 0.092±0.324; NS
| | LAZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=51 42) | . | −0.131±0.484 vs −0.092±0.391; NS
| | WLZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=51 42) | . | 0.169±0.153 vs 0.151±0.632; NS
| Iron supplement from ~5-7 mo to ~9-11 mo (1 mg/kg/d) vs Iron supplement from ~5-7 mo to ~9-11 mo (25 mg/wk) | Weight change (mean ± SD, kg) from ~5-7 mo to ~9-11 mo (N=51,42) | . | 1.201±0.503 vs 1.379±0.524; NS
| | Length change (mean ± SD, cm) from ~5-7 mo to ~9-11 mo (N=51,42) | . | 5.15±1.14 vs 5.61±1.09; NS
| | WAZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=51,42) | . | 0.015±0.487 vs 0.167±0.481; NS
| | LAZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=51,42) | . | −0.131±0.484 vs 0.072±0.497; NS
| | WLZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=51,42) | . | 0.169±0.153 vs 0.151±0.632; NS
| Iron supplement from ~5-7 mo to ~9-11 mo (2 mg/kg/d) vs Iron supplement from ~5-7 mo to ~9-11 mo (25 mg/wk) | Weight change (mean ± SD, kg) from ~5-7 mo to ~9-11 mo (N=42,42) | . | 1.267±0.372 vs 1.379±0.524; NS
| | Length change (mean ± SD, cm) from ~5-7 mo to ~9-11 mo (N=42,42) | . | 5.22±1.01 vs 5.61±1.09; NS
| | WAZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=42,42) | . | 0.092±0.324 vs 0.167±0.481; NS
| | LAZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=42,42) | . | −0.092±0.391 vs 0.072±0.497; NS
| | WLZ change (mean ± SD) from ~5-7 mo to ~9-11 mo (N=42,42) | . | 0.151±0.632 vs 0.151±0.632; NS
Dewey 2002 ^4^; RCT; Sweden | Placebo from 4 to 6 mo and iron supplement from 6 to 9 mo (1 mg/kg/d) vs Iron supplement from 4 to 9 mo (1 mg/kg/d) | Weight gain (mean ± SE, g) | .
Dewey 2002 ^4^; RCT; Sweden | Placebo from 4 to 6 mo and iron supplement from 6 to 9 mo (1 mg/kg/d) vs Iron supplement from 4 to 9 mo (1 mg/kg/d) | from 4 to 6 mo (N=34, 31) | . | 860 ± 54 vs 880 ± 57; NS
| | from 6 to 9 mo (N=30, 30) | . | 1137 ± 75 vs 1054 ± 75; NS
| | from 4 to 9 mo (N=30, 30) | . | 2013 ± 100 vs 1925 ± 101; NS
| | Length gain (mean ± SE, cm)
| | from 4 to 6 mo (N=34, 31) | . | 3.02 ± 0.15 vs 3.37 ± 0.16; NS
| | from 6 to 9 mo (N=30, 30) | . | 4.22 ± 0.21 vs 4.00 ± 0.21; NS
| | from 4 to 9 mo (N=30, 30) | . | 7.14 ± 0.23 vs 7.31 ± 0.23; NS
| | Change in head circumference (mean ± SE, cm)
| | from 4 to 6 mo (N=34, 31) | . | 1.74 ± 0.06 vs 1.57 ± 0.06; NS
| | from 6 to 9 mo (N=30, 30) | . | 2.09 ± 0.07 vs 2.00 ± 0.07; NS
| | from 4 to 9 mo (N=30, 30) | 3.84 ± 0.09 vs 3.56 ± 0.09; p=0.03 | .
Iron from supplement compared to iron from fortified food
Capozzi 2011 ^2^; PC or NRCT or RCT^§^; Italy | EBF 5-6 mo and weaned with iron-fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | Weight (mean ± SD, kg)
Capozzi 2011 ^2^; PC or NRCT or RCT^§^; Italy | EBF 5-6 mo and weaned with iron-fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | In males (N=12, 14)
Capozzi 2011 ^2^; PC or NRCT or RCT^§^; Italy | EBF 5-6 mo and weaned with iron-fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | at 6 mo | 7.3 ± 0.8 vs 7.2 ± 0.8; p<0.05 | .
| | at 12 mo | . | 9.1 ± 0.2 vs 9.4 ± 1.5; NS
| | at 18 mo | . | 12 ± 0.9 vs 12.6 ± 0.9; NS
| | at 24 mo | . | 12.3 ± 1.8 vs 12.9 ± 2.1; NS
| | In females (N=16, 12)
| | at 6 mo | 7 ± 0.6 vs 7.2 ± 0.9; p<0.05 | .
| | at 12 mo | . | 9 ± 1 vs 9.1± 1.1; NS
| | at 18 mo | . | 10.5 ± 0.9 vs 11.9 ± 1.8; NS
| | at 24 mo | 11.2 ± 0.7 vs 12.8 ± 1.1; p<0.05 | .
| | Length (mean ± SD, cm) at 6 mo
| | In males (N=12, 14)
| | at 6 mo | . | 67.1 ± 0.3 vs 67.1 ± 0.6; NS
| | at 12 mo | 74.5 ± 0.9 vs 73.4 ± 0.7; p<0.05 | .
| | at 18 mo | 80.2 ± 2.2 vs 78.1 ± 1.2; p<0.05 | .
| | at 24 mo | 86.9 ± 1.2 vs 83.5 ± 1.9; p<0.05 | .
| | In females (N=16, 12)
| | at 6 mo | . | 64.5 ± 1.3 vs 63.9 ± 1.3; NS
| | at 12 mo | 72 ± 1.6 vs 70 ± 2.1; p<0.05 | .
| | at 18 mo | 78.2 ± 1.2 vs 77.1 ± 0.6; p<0.05 | .
| | at 24 mo | 83.5 ± 1.9 vs 82.1 ± 1.9; p<0.05 | .
| Iron-fortified FF and weaned at 5-6 mo with iron-fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | Weight (mean ± SD, kg)
| Iron-fortified FF and weaned at 5-6 mo with iron-fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | In males (N=14, 14)
| Iron-fortified FF and weaned at 5-6 mo with iron-fortified food vs EBF 5-6 mo (weaning CF NR) and given iron supplement from 4 to 9 mo (1 mg/kg/d) | at 6 mo | 7.2 ± 0.1 vs 7.2 ± 0.8; p<0.05 | .
| | at 12 mo | . | 9.3 ± 0.9 vs 9.4 ± 1.5; NS
| | at 18 mo | . | 12.5 ± 0.7 vs 12.6 ± 0.9; NS
| | at 24 mo | . | 12.7 ± 1.4 vs 12.9 ± 2.1; NS
| | In females (N=18, 12)
| | at 6 mo | 7.1 ± 0.9 vs 7.2 ± 0.9; p<0.05 | .
| | at 12 mo | . | 9 ± 0.8 vs 9.1± 1.1; NS
| | at 18 mo | . | 11 ± 0.7 vs 11.9 ± 1.8; NS
| | at 24 mo | . | 12.4 ± 1.4 vs 12.8 ± 1.1; NS
| | Length (mean ± SD, cm) at 6 mo
| | In males (N=14, 14)
| | at 6 mo | . | 67.2 ± 1.5 vs 67.1 ± 0.6; NS
| | at 12 mo | 75.1 ± 0.9 vs 73.4 ± 0.7; p<0.05 | .
| | at 18 mo | 80.1 ± 2.3 vs 78.1 ± 1.2; p<0.05 | .
| | at 24 mo | . | 84.9 ±2.6 vs 83.5 ± 1.9; NS
| | In females (N=18, 12)
| | at 6 mo | . | 64.3 ± 1.6 vs 63.9 ± 1.3; NS
| | at 12 mo | 71.9 ± 1.6 vs 70 ± 2.1; p<0.05 | .
| | at 18 mo | 78.1 ± 1.6 vs 77.1 ± 0.6; p<0.05 | .
| | at 24 mo | . | 82.6 ± 1.6 vs 82.1 ± 1.9; NS
Szymley-Gay 2016 ^8^; RCT; Sweden | High-iron formula from 6 to 7.5 mo (6.6 mg/d) vs No-added-iron formula and iron supplement from 6 to 7.5 mo (6.6 mg/d) | Change in weight (mean (95% CI), kg) from 6 to 7.5 mo (N=23, 20) | . | 0.0 (−0.1, 0.1); p=0.956
| | Change in WAZ from 6 to 7.5 mo (N=23, 20) | . | NS; data NR
| | Change in length (mean (95% CI), cm) from 6 to 7.5 mo (N=23, 20) | . | −0.3 (−0.9, 0.3); p=0.369
| | Change in LAZ from 6 to 7.5 mo (N=23, 20) | . | NS; data NR
| | Change in head circumference (mean (95% CI), cm) from 6 to 7.5 mo (N=23, 20) | −0.2 (−0.4, 0.0); p=0.046 | .
| | Change in HCAZ from 6 to 7.5 mo (N=23, 20) | . | NS; data NR
| | Change in knee-heel length (mean (95% CI), mm) from 6 to 7.5 mo (N=23, 20) | . | −0.4 (−2.7, 1.9); p=0.751
| No-added-iron formula and iron supplement from 6 to 7.5 mo (6.6 mg/d) vs Low-iron formula from 6 to 7.5 mo (1.3 mg/d) | Change in weight (mean (95% CI), kg) from 6 to 7.5 mo (N=23, 20) | . | 0.0 (−0.2, 0.1); p=0.696
| | Change in WAZ from 6 to 7.5 mo (N=23, 20) | . | NS; data NR
| | Change in length (mean (95% CI), cm) from 6 to 7.5 mo (N=23, 20) | . | 0.0 (−0.6, 0.6); p=0.991
| | Change in LAZ from 6 to 7.5 mo (N=23, 20) | . | NS; data NR
| | Change in head circumference (mean (95% CI), cm) from 6 to 7.5 mo (N=22, 20) | . | 0.0 (−0.2, 0.1); p=0.709
| | Change in HCAZ from 6 to 7.5 mo (N=22, 20) | . | NS; data NR
| | Change in knee-heel length (mean (95% CI), mm) from 6 to 7.5 mo (N=23, 20) | . | −0.6 (−2.9, 1.8); p=0.632
Ziegler 2009 ^9^; RCT; US | Iron supplement from 4 to 9 mo (7.5 mg/d) vs iron from iron-fortified cereal from 4 to 9 mo (~7 mg/d) | Weight (mean ± SD, g) at 9 mo
Ziegler 2009 ^9^; RCT; US | Iron supplement from 4 to 9 mo (7.5 mg/d) vs iron from iron-fortified cereal from 4 to 9 mo (~7 mg/d) | In male subsample (N=18, 19) | . | 9114 ± 970 vs 8883 ± 755; NS
| | In female subsample (N=23, 19) | . | 8197 ± 732 vs 8496 ± 871; NS
| | Weight gain (mean ± SD, g/d) from 4 to 9 mo (N=41, 38) | . | 12.18 (SD NR) vs 13.13 (SD NR); NS
| | In male subsample (N=18, 19) | . | 12.7 ± 2.39 vs 13.0 ± 2.57; NS
| | In female subsample (N=23, 19) | . | 11.6 ± 3.23 vs 13.2 ± 2.73; NS
| | Length (mean ± SD, cm) at 9 mo | .
| | In male subsample (N=18, 19) | | 72.0 ± 1.92 vs 71.7 ± 1.50; NS
| | In female subsample (N=23, 19) | . | 69.2 ± 1.79 vs 69.7 ± 2.32; NS
| | Length gain (mean ± SD, mm/d) from 4 to 9 mo (N=41, 38) | . | 0.484 (SD NR) vs 0.503 (SD NR); NS
| | In male subsample (N=18, 19) | . | 0.50 ± 0.071 vs 0.50 ± 0.073; NS
| | In female subsample (N=23, 19) | . | 0.47 ± 0.062 vs 0.50 ± 0.055; NS

* Abbreviations: BMIz – body mass index Z score, CI – confidence interval, CF – complementary foods, EBF – exclusively breastfed, FF – formula fed, HAZ – height-for-age Z score, HCAZ – head circumference-for-age Z score, LAZ – length-for-age Z score, NR – not reported, NRCT – non randomized controlled trial, PC – prospective cohort, RCT–randomized controlled trial, SD –standard deviation, SE – standard error, WAZ – weight-for-age Z score, WHZ – weight-for-height Z score, WLZ – weight-for-length Z score

† Interventions and comparators, from the articles included in the body of evidence, which compare iron from supplements with a control, a placebo, a different level of iron from supplements, or iron from fortified foods

‡ Outcomes, from the articles included in the body of evidence, which address growth, size, or body composition

§ Authors did not clearly describe the study design; we cannot tell whether and to which groups infants were randomly allocated

Table 4 Risk of bias for randomized controlled trials examining iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition^*^,^†^

| Randomization | Identification of participants - randomization | Deviations from intended interventions | Missing outcome data | Outcome measurement | Selection of the reported result
da Silva, 2008^3^ | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns | Low
Dewey, 2002^4^ | Low | Low | Low | Low | Low | Low
Friel, 2003^5^ | Some Concerns | Low | Some Concerns | High | Some Concerns | Low
Hacihamdioglu, 2013^6^ | High | Low | Some Concerns | Some Concerns | Some Concerns | Low
Lozoff, 2016^7^ | High | Low | Low | Some Concerns | Some Concerns | Low
Szymley-Gay, 2016^8^ | Low | Low | Some Concerns | Some Concerns | Some Concerns | Low
Ziegler, 2009^9^ | Some Concerns | Low | Some Concerns | Some Concerns | Some Concerns | Low
Ziegler, 2009^10^ | High | Low | Low | Some Concerns | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, some concerns, or high determined using the “Cochrane Risk-of-bias 2.0” (RoB 2.0) (https://www.riskofbias.info/welcome/rob-2-0-tool) (August 2016 version)” ( Higgins JPT, Sterne JAC, Savović J, Page MJ, Hróbjartsson A, Boutron I, Reeves B, Eldridge S. A revised tool for assessing risk of bias in randomized trials In: Chandler J, McKenzie J, Boutron I, Welch V (editors). Cochrane Methods. Cochrane Database of Systematic Reviews 2016, Issue 10 (Suppl 1). 10.1002/14651858.CD201601. )

Table 5 Risk of bias for the non-randomized controlled trial examining iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition^*^,^†^

| Confounding | Selection of participants | Classification of interventions | Deviations from intended interventions | Missing data | Outcome measurement | Selection of the reported result
Azeredo 2010^1^ | Serious | Serious | Low | Low | Serious | Low | Low

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias in Non-randomized Studies of Interventions (ROBINS-I) tool” (https://www.riskofbias.info/welcome/home/current-version-of-robins-i) ( Sterne JAC, Hernán MA, Reeves BC, Savović J, Berkman ND, Viswanathan M, Henry D, Altman DG, Ansari MT, Boutron I, Carpenter JR, Chan AW, Churchill R, Deeks JJ, Hróbjartsson A, Kirkham J, Jüni P, Loke YK, Pigott TD, Ramsay CR, Regidor D, Rothstein HR, Sandhu L, Santaguida PL, Schünemann HJ, Shea B, Shrier I, Tugwell P, Turner L, Valentine JC, Waddington H, Waters E, Wells GA, Whiting PF, Higgins JPT. ROBINS-I: a tool for assessing risk of bias in non-randomized studies of interventions. BMJ 2016; 355; i4919; doi: 10.1136/bmj.i4919. )

Table 6 Risk of bias for the observational study examining iron from supplements consumed during infancy and toddlerhood and growth, size, and body composition^*^,^†^

| Confounding | Selection of participants | Classification of exposures | Deviations from intended exposures | Missing data | Outcome measurement | Selection of the reported result
Capozzi 2011^2^,^‡^ | Serious | No information | Critical | Moderate | No information | Moderate | Serious

* A detailed description of the methodology used for assessing risk of bias is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

† Possible ratings of low, moderate, serious, critical, or no information determined using the “Risk of Bias for Nutrition Observational Studies” tool (RoB-NObs) ( Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC. )

‡ Insufficient reporting made it difficult to determine whether this study was a randomized controlled trial, non-randomized controlled trial, or prospective cohort study; we have assessed its risk of bias as a prospective cohort study

### Research recommendations

- Evaluate how to best identify and treat infants who become iron deficient before 6 months of age, including populations with racial and ethnic diversity.
- Investigate the biological mechanisms by which iron supplementation during infancy may affect growth, including potential effects on morbidity, the microbiome, zinc status, and oxidative stress or lipid peroxidation.

### Included articles

1 Azeredo CM, Cotta RM, Sant’Ana LF, . Greater effectiveness of daily iron supplementation scheme in infants. Rev Saude Publica. 2010;44(2):230–239.doi: 10.1590/s0034-89102010000200002.20339622
2 Capozzi L, Russo R, Bertocco F, Ferrara D, Ferrara M. Effect on haematological and anthropometric parameters of iron supplementation in the first 2 years of life. Risks and benefits. Hematology. 2011;16(5):261–264.doi: 10.1179/102453311X13085644679980.21902888
3 da Silva G, Franceschini Sdo C, Sigulem DM. Growth in non-anemic infants supplemented with different prophylactic iron doses. J Pediatr (Rio J). 2008;84(4):365–372.doi: 10.2223/JPED.1817.18688547
4 Dewey KG, Domellof M, Cohen RJ, Landa Rivera L, Hernell O, Lonnerdal B. Iron supplementation affects growth and morbidity of breast-fed infants: results of a randomized trial in Sweden and Honduras. J Nutr. 2002;132(11):3249–3255.doi: 10.1093/jn/132.11.3249.12421836
5 Friel JK, Aziz K, Andrews WL, Harding SV, Courage ML, Adams RJ. A double-masked, randomized control trial of iron supplementation in early infancy in healthy term breast-fed infants. J Pediatr. 2003;143(5):582–586.doi: 10.1067/S0022-3476(03)00301-9.14615726
6 Hacihamdioglu DO, Kurekci AE, Gursel O, . Evaluation of lipid peroxidation and antioxidant system in healthy iron-replete infants receiving iron prophylaxis. Nutrition. 2013;29(1):138–142.doi: 10.1016/j.nut.2012.05.009.23116775
7 Lozoff B, Jiang Y, Li X, . Low-Dose Iron Supplementation in Infancy Modestly Increases Infant Iron Status at 9 Mo without Decreasing Growth or Increasing Illness in a Randomized Clinical Trial in Rural China. J Nutr. 2016;146(3):612–621.doi: 10.3945/jn.115.223917.26791556
8 Szymlek-Gay EA, Domellof M, Hernell O, . Mode of oral iron administration and the amount of iron habitually consumed do not affect iron absorption, systemic iron utilisation or zinc absorption in iron-sufficient infants: a randomised trial. Br J Nutr. 2016;116(6):1046–1060.doi: 10.1017/S0007114516003032.27546308
9 Ziegler EE, Nelson SE, Jeter JM. Iron status of breastfed infants is improved equally by medicinal iron and iron-fortified cereal. Am J Clin Nutr. 2009;90(1):76–87.doi: 10.3945/ajcn.2008.27350.19458014
10 Ziegler EE, Nelson SE, Jeter JM. Iron supplementation of breastfed infants from an early age. Am J Clin Nutr. 2009;89(2):525–532.doi: 10.3945/ajcn.2008.26591.19073791

ii National Institutes of Health Office of Dietary Supplements. Dietary Supplement Health and Education Act of 1994 Public Law 103-417 103rd Congress: Sec. 3. Definitions. https://ods.od.nih.gov/About/DSHEA_Wording.aspx#sec3 Published October 25, 1994. Accessed May 18, 2020

iii A detailed description of the methodology used for grading the strength of the evidence is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews and in Part C of the following reference: Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

iv Reported in: Domellöf, M., Cohen, R. J., Dewey, K. G., Hernell, O., Rivera, L. L., & Lönnerdal, B. (2001). Iron supplementation of breast-fed Honduran and Swedish infants from 4 to 9 months of age. The Journal of pediatrics, 138(5), 679–687.11343043