# List of abbreviations

Abbreviation: Full name
ACM: All-cause mortality
CNPP: Center for Nutrition Policy and Promotion
CVD: Cardiovascular disease
DPS: Division of Prevention Science
FNS: Food and Nutrition Service
HDI: Human development index
HHS: United States Department of Health and Human Services
NESR: Nutrition Evidence Systematic Review
OASH: Office of the Assistant Secretary for Health
ODPHP: Office of Disease Prevention and Health Promotion
ONGA: Office of Nutrition Guidance and Analysis
PCS: Prospective cohort study
RCT: Randomized controlled trial
UK: United Kingdom
USDA: United States Department of Agriculture