# METHODOLOGY

The NESR team used its rigorous, protocol-driven methodology to support the 2020 Dietary Guidelines Advisory Committee in conducting this systematic review.

NESR’s systematic review methodology involves:

- Developing a protocol,
- Searching for and selecting studies,
- Extracting data from and assessing the risk of bias of each included study,
- Synthesizing the evidence,
- Developing conclusion statements,
- Grading the evidence underlying the conclusion statements, and
- Recommending future research.

A detailed description of the methodology used in conducting this systematic review is available on the NESR website: https://nesr.usda.gov/2020-dietary-guidelines-advisory-committee-systematic-reviews, and can be found in the 2020 Dietary Guidelines Advisory Committee Report, Part C: Methodology.^ix^ This systematic review was peer reviewed by Federal scientists, and information about the peer review process can also be found in the Committee’s Report, Part C. Methodology. Additional information about this systematic review, including a description of and rationale for any modifications made to the protocol can be found in the in the 2020 Dietary Guidelines Advisory Committee Report, Chapter 11. Alcoholic Beverages.

Below are details of the final protocol for the systematic review described herein, including the:

- Analytic framework
- Literature search and screening plan
- Literature search and screening results

## ANALYTIC FRAMEWORK

The analytic framework (Figure 1) illustrates the overall scope of the systematic review, including the population, the interventions and/or exposures, comparators, and outcomes of interest. It also includes definitions of key terms and identifies key confounders considered in the systematic review. The inclusion and exclusion criteria that follow provide additional information about how parts of the analytic framework were defined and operationalized for the review.

Figure 1 Analytic framework

An analytic framework visually represents the overall scope of the systematic review question, and depicts the contributing elements that were examined and evaluated, including the target population, exposure, comparison, outcomes, and key confounders. This is the analytic framework for the systematic review question on alcohol consumption and all-cause mortality. For this systematic review, the target population considered was adults ages 21 years and older. The interventions or exposures considered were average consumption of alcoholic beverages and the pattern of consumption of alcoholic beverages (i.e., the number of drinks per drinking day or drinks per drinking occasion). The primary comparator of interest was differing average alcohol consumption or patterns among those who currently drink alcohol. The secondary comparison was between those who currently drink alcohol and those who have never consumed alcohol (i.e., lifetime abstainers). The outcome considered was all-cause mortality. The key confounders were sex, age, race/ethnicity, SES (income, education, health insurance, preventive health care access), eating pattern or diet quality, physical activity, and smoking. A key confounder specific to the average consumption exposure was the pattern of consumption. A key confounder specific to pattern of consumption exposure was average consumption. Other factors to be considered were total energy intake (ideally without alcohol), age distribution of the study sample, anthropometry, hypertension, blood pressure, diabetes, glucose, lipids, medications, family history of chronic disease, and beverage type (e.g., beer, wine, spirits).

## LITERATURE SEARCH AND SCREENING PLAN

### Inclusion and exclusion criteria

Table 3 provides the inclusion and exclusion criteria for the systematic review. The inclusion and exclusion criteria are a set of characteristics used to determine which articles identified in the literature search were included in or excluded from the systematic review.

Table 3 Inclusion and exclusion criteria

Category | Inclusion Criteria | Exclusion Criteria
Study design | - Randomized controlled trials; - Mendelian randomization studies; - Non-randomized controlled trials including quasi-experimental and controlled before-and-after studies; - Prospective cohort studies; - Retrospective cohort studies; - Nested case-control studies | - Uncontrolled trials; - Case-control studies; - Cross-sectional studies; - Uncontrolled before-and-after studies; - Narrative reviews; - Systematic reviews; - Meta-analyses
Sample size | - Observational studies enrolling >1,000 participants | - Observational studies enrolling <1,000 participants
Intervention/exposure | Average consumption of alcoholic beverages; Per occasion consumption of alcohol beverages (i.e., number of drinks per drinking day or drinks per drinking occasion); - Information on type of beverage (e.g., beer, wine, spirits) will be collected if available | - Data on ‘non-drinker’ groups where never and former drinkers are combined
Comparator | [underlined: Primary]; - Comparisons across different average alcohol consumption or pattern of alcohol consumption among current drinkers; [underlined: Secondary]; - Comparisons between never drinkers and current drinkers | No comparator; - Comparisons with never and former drinkers as a combined ‘non-drinker’ group
Outcomes | - All-cause mortality (i.e. total mortality): the total number of deaths from all causes during a specific time period.; - (Ideally stratified by sex) | - Studies that only report cause-specific mortality (total number of deaths from a specific disease, such as cardiovascular disease or cancer)
Date of publication | - January 2010 – March 2020 | - Articles published prior to January 2010
Publication status | - Articles published in peer-reviewed journals | - Articles not published in peer-reviewed journals, including unpublished data, manuscripts, reports, abstracts, pre-prints, and conference proceedings
Language of publication | - Articles published in English | - Articles published in languages other than English
Country ^x^ | - Studies conducted in Very High or High Human Development Countries | - Studies conducted in Medium or lower Human Development Countries
Study participants | - Human participants; - Males; - Females | - Animal subjects; - Hospitalized samples
Age of study participants | - Primarily adults 21y and older; - Studies that enroll some participants under 21 years old | - Studies that exclusively enroll participants under 21 years old
Health status of study participants | - Studies that enroll participants who are healthy and/or at risk for chronic disease, including those with obesity; - Studies that enroll some participants diagnosed with a disease | - Studies that exclusively enroll participants diagnosed with a disease or hospitalized with an illness or injury. (For this criterion, studies that exclusively enroll subjects with obesity will not be excluded)

### Electronic databases and search terms

Listed below are the databases searched to identify all potentially relevant articles that have been published to address the update to the existing systematic review.

#### PubMed

- Provider: U.S. National Library of Medicine
- Date(s) Searched: March 11, 2020
- Date range searched: January 1, 2000-March 11, 2020
- Search Terms:
  - #1 - “Alcohol-Induced Disorders”[Mesh] OR alcohol intake*[tiab] OR alcohol consum*[tiab] OR “Alcohol Drinking”[Mesh] OR alcohol drink*[tiab] OR “Alcoholic Beverages”[Mesh] OR alcoholic beverage*[tiab] OR beer*[tiab] OR wine*[tiab] OR liquor[tiab] OR liqueur*[tiab] OR spirits[tiab] OR “Ethanol”[Mesh] OR ethanol[tiab]
  - #2 - “Mortality”[Mesh] OR “mortality” [Subheading] OR mortality[tiab]
  - #3 - (#1 AND #2) NOT (“Animals”[Mesh] NOT (“Animals”[Mesh] AND “Humans”[Mesh])) NOT (editorial[ptyp] OR comment[ptyp] OR news[ptyp] OR letter[ptyp] OR review[ptyp] OR systematic review[ptyp] OR systematic review[ti] OR meta-analysis[ptyp] OR meta-analysis[ti] OR meta-analyses[ti] OR retracted publication[ptyp] OR retraction of publication[ptyp] OR retraction of publication[tiab] OR retraction notice[ti]) Filters: Publication date from 2000/01/01 to 2020/03/11; English

#### Cochrane Central Register of Controlled Trials (CENTRAL)

- Provider: John Wiley & Sons
- Date(s) Searched: March 11, 2020
- Date range searched: January 1, 2000-March 11, 2020
- Search Terms:
  - #1 - [mh “Alcohol-Induced Disorders”] OR [mh “Alcohol Drinking”] OR [mh “Alcoholic Beverages”] OR [mh “Ethanol”]
  - #2 - (“alcohol intake*” OR “alcohol consum*” OR “alcohol drink*” OR “alcoholic beverage*” OR beer* OR wine* OR liquor OR liqueur* OR spirits OR ethanol):ti,ab,kw
  - #3 - #1 OR #2
  - #4 - ([mh “Mortality”] OR [mh /MO] OR mortality):ti,ab,kw”
  - #5 - #3 AND #4
  - #6 - #3 AND #4” with Publication Year from 2000 to 2020, in Trials (Word variations have been searched)

#### Embase

- Provider: Elsevier
- Date(s) Searched: March 11, 2020
- Date range searched: January 1, 2000-March 11, 2020
- Search Terms:
  - #1 - ‘alcoholism’/exp OR ‘drinking behavior’/de OR ‘alcoholic beverage’/exp OR ‘alcohol’/de
  - #2 - ‘alcohol intake*’:ab,ti OR ‘alcohol consum*’:ab,ti OR ‘alcohol drink*’:ab,ti OR ‘alcoholic beverage*’:ab,ti OR beer*:ab,ti OR wine*:ab,ti OR liquor:ab,ti OR liqueur*:ab,ti OR spirits:ab,ti
  - #3 - #1 OR #2
  - #4 - ‘mortality’/exp OR mortality:ab,ti
  - #5 - #3 AND #4
  - #6 - #3 AND #4 AND ([article]/lim OR [article in press]/lim) AND [humans]/lim AND [english]/lim AND [2000-2020]/py NOT ([conference abstract]/lim OR [conference paper]/lim OR [conference review]/lim OR [editorial]/lim OR [erratum]/lim OR [letter]/lim OR [note]/lim OR [review]/lim OR [systematic review]/lim OR [meta analysis]/lim)

## LITERATURE SEARCH AND SCREENING RESULTS

The flow chart (Figure 2) below illustrates the literature search and screening results for articles examining the systematic review question. The results of the electronic database searches, after removal of duplicates, were screened independently by two NESR analysts using a step-wise process by reviewing titles, abstracts, and full-texts to determine which articles met the inclusion criteria. Refer to Table 4 for the rationale for exclusion for each excluded full-text article. A manual search was done to find articles that were not identified when searching the electronic databases; all manually identified articles are also screened to determine whether they meet criteria for inclusion.

Figure 2 Flow chart of literature search and screening results

This flow chart illustrates the literature search and screening results for articles examining the relationship between alcohol consumption and all-cause mortality. The literature search yielded 10,422 articles. During title screening, 8458 articles were screened out. During abstract screening, 1606 articles were screened out. During full-text screening, 299 articles were screened out. During the hand search, 1 additional article was identified to include. A total of 60 articles were included in the systematic review at the end of the search and screening process.

### Excluded articles

The table below lists the articles excluded after full-text screening, and includes categories of inclusion and exclusion criteria (see Table 3) that studies were excluded. At least one reason for exclusion is provided for each article, though this may not reflect all possible reasons for exclusion. Information about articles excluded after title and abstract screening is available upon request.

Table 4 Articles excluded after full text screening with rationale for exclusion

| Citation | Rationale
1 | Aburto JM, van Raalte A. Lifespan dispersion in times of life expectancy fluctuation: the case of Central and Eastern Europe. Demography. 2018. 55(6):2071-2096. doi:10.1007/s13524-018-0729-9. | Study Design; Intervention/Exposure
2 | Agahi N, Kelfve S, Lennartsson C, Kareholt I. Alcohol consumption in very old age and its association with survival: A matter of health and physical function. Drug Alcohol Depend. 2016. 159:240-5. doi:10.1016/j.drugalcdep.2015.12.022. | Sample size
3 | Akbaraly TN, Ferrie JE, Berr C, Brunner EJ, Head J, Marmot MG, Singh-Manoux A, Ritchie K, Shipley, MJ, Kivimaki, M. Alternative Healthy Eating Index and mortality over 18 y of follow-up: results from the Whitehall II cohort. Am J Clin Nutr. 2011. 94(1):247-53. doi:10.3945/ajcn.111.013128. | Comparator
4 | AlGhatrif M, Markides KS, Kuo YF, Ray LA, Moore AA. The effect of prevalent cardiovascular conditions on the association between alcohol consumption and mortality among older Mexican American men. Ethn Dis. 2013. 23(2):168-74. | Sample size
5 | Arndt V, Rothenbacher D, Krauledat R, Daniel U, Brenner H. Age, alcohol consumption, and all-cause mortality. Ann Epidemiol. 2004. 14(10):750-3. doi:10.1016/j.annepidem.2004.01.004. | Publication Date
6 | Baer HJ, Glynn RJ, Hu FB, Hankinson SE, Willett WC, Colditz GA, Stampfer M, Rosner B. Risk factors for mortality in the nurses’ health study: a competing risks analysis. Am J Epidemiol. 2011. 173(3):319-29. doi:10.1093/aje/kwq368. | Comparator
7 | Baglietto L, English DR, Hopper JL, Powles J, Giles GG. Average volume of alcohol consumed, type of beverage, drinking pattern and the risk of death from all causes. Alcohol Alcohol. 2006. 41(6):664-71. doi:10.1093/alcalc/agl087. | Publication Date
8 | Bahat G, Tufan F, Bahat Z, Tufan A , Aydin Y, Akpinar TS, Erten N, Karan MA. Observational cohort study on correlates of mortality in older community-dwelling outpatients: The value of functional assessment. Geriatr Gerontol Int. 2015. 15(11):1219-26. doi:10.1111/ggi.12422. | Intervention/Exposure
9 | Bartak M. Alcohol Consumption and Cause-Specific Mortality in Russia: A View From the Czech Republic. J Stud Alcohol Drugs. 2019. 80(5):503-504. | Study Design; Publication Status
10 | Batty GD, Lewars H, Emslie C, Gale CR, Hunt K. Internationally recognized guidelines for ‘sensible’ alcohol consumption: is exceeding them actually detrimental to health and social circumstances? Evidence from a population-based cohort study. J Public Health (Oxf). 2009. 31(3):360-5. doi:10.1093/pubmed/fdp063. | Publication Date
11 | Bazzano LA, Gu D, Reynolds K, Chen J, Wu X, Chen CS, Duan X, Chen J, He J. Alcohol consumption and risk of coronary heart disease among Chinese men. Int J Cardiol. 2009. 135(1):78-85. doi:10.1016/j.ijcard.2008.03.038. | Outcome
12 | Behrens G, Leitzmann MF, Sandin S, Lof M, Heid IM, Adami HO, Weiderpass E. The association between alcohol consumption and mortality: the Swedish women’s lifestyle and health study. Eur J Epidemiol. 2011. 26(2):81-90. doi:10.1007/s10654-011-9545-x. | Comparator
13 | Bellavia A, Tektonidis TG, Orsini N, Wolk A, Larsson SC. Quantifying the benefits of Mediterranean diet in terms of survival. Eur J Epidemiol. 2016. 31(5):527-30. doi:10.1007/s10654-016-0127-9. | Intervention/Exposure
14 | Bobak M, Murphy M, Rose R, Marmot M. Determinants of adult mortality in Russia: estimates from sibling data. Epidemiology. 2003. 14(5):603-11. doi:10.1097/01.ede.0000082000.75818.4d. | Publication Date
15 | Bondonno NP, Lewis JR, Blekkenhorst LC, Bondonno CP, Shin JH, Croft KD, Woodman RJ, Wong G, Lim WH, Gopinath B, Flood VM, Russell J, Mitchell P, Hodgson JM. Association of flavonoids and flavonoid-rich foods with all-cause mortality: The Blue Mountains Eye Study. Clin Nutr. 2020. 39(1):141-150. doi:10.1016/j.clnu.2019.01.004. | Intervention/Exposure
16 | Boyle SH, Mortensen L, Gronbaek M, Barefoot JC. Hostility, drinking pattern and mortality. Addiction. 2008. 103(1):54-9. doi:10.1111/j.1360-0443.2007.02024.x. | Publication Date
17 | Breslow RA, Graubard BI. Prospective study of alcohol consumption in the United States: quantity, frequency, and cause-specific mortality. Alcohol Clin Exp Res. 2008. 32(3):513-21. doi:10.1111/j.1530-0277.2007.00595.x. | Outcome
18 | Bridevaux IP, Bradley KA, Bryson CL, McDonell MB, Fihn SD. Alcohol screening results in elderly male veterans: association with health status and mortality. J Am Geriatr Soc. 2004. 52(9):1510-7. doi:10.1111/j.1532-5415.2004.52414.x. | Intervention/Exposure
19 | Britton A, Marmot M. Different measures of alcohol consumption and risk of coronary heart disease and all-cause mortality: 11-year follow-up of the Whitehall II Cohort Study. Addiction. 2004. 99(1):109-16. doi:10.1111/j.1360-0443.2004.00530.x. | Publication Date
20 | Britton A. Moderate alcohol consumption and total mortality risk: Do not advocate drinking for ‘health benefits’. Nutr Metab Cardiovasc Dis. 2019. 29(10):1009-1010. doi:10.1016/j.numecd.2019.06.007. | Study Design; Publication Status
21 | Buckland G, Agudo A, Travier N, Huerta, JM, Cirera L, Tormo, MJ, Navarro C, Chirlaque, MD, Moreno-Iribas C, Ardanaz E, Barricarte A, Etxeberria J, Marin P, Quiros, JR, Redondo, ML, Larranaga N, Amiano P, Dorronsoro M, Arriola L, Basterretxea M, Sanchez, MJ, Molina E, Gonzalez CA. Adherence to the Mediterranean diet reduces mortality in the Spanish cohort of the European Prospective Investigation into Cancer and Nutrition (EPIC-Spain). Br J Nutr. 2011. 106(10):1581-91. doi:10.1017/s0007114511002078. | Intervention/Exposure; Comparator
22 | Burke V, Zhao Y, Lee AH, Hunter E, Spargo RM, Gracey M, Smith RM, Beilin LJ, Puddey IB. Health-related behaviours as predictors of mortality and morbidity in Australian Aborigines. Prev Med. 2007. 44(2):135-42. doi:10.1016/j.ypmed.2006.09.008. | Publication Date
23 | Byun W, Sieverdes JC, Sui X, Hooker SP, Lee CD, Church TS, Blair SN. Effect of positive health factors and all-cause mortality in men. Med Sci Sports Exerc. 2010. 42(9):1632-8. doi:10.1249/MSS.0b013e3181d43f29. | Comparator
24 | Carlsson AC, Theobald H, Wandell PE. Health factors and longevity in men and women: a 26-year follow-up study. Eur J Epidemiol. 2010. 25(8):547-51. doi:10.1007/s10654-010-9472-2. | Sample size
25 | Carlsson AC, Wandell PE, Gigante B, Leander K, Hellenius ML, de Faire U. Seven modifiable lifestyle factors predict reduced risk for ischemic cardiovascular disease and all-cause mortality regardless of body mass index: a cohort study. Int J Cardiol. 2013. 168(2):946-52. doi:10.1016/j.ijcard.2012.10.045. | Intervention/Exposure
26 | Carpenter C, Dobkin C. The Effect of Alcohol Consumption on Mortality: Regression Discontinuity Evidence from the Minimum Drinking Age. Am Econ J Appl Econ. 2009. 1(1):164-182. doi:10.1257/app.1.1.164. | Intervention/Exposure
27 | Chen LY, Hardy CL. Alcohol consumption and health status in older adults: a longitudinal analysis. J Aging Health. 2009. 21(6):824-47. doi:10.1177/0898264309340688. | Publication Date
28 | Cheung MR. Lack of health insurance increases all cause and all cancer mortality in adults: an analysis of National Health and Nutrition Examination Survey (NHANES III) data. Asian Pac J Cancer Prev. 2013. 14(4):2259-63. doi:10.7314/apjcp.2013.14.4.2259. | Comparator
29 | Chikritzhs T, Stockwell T, Jonas H, Stevenson C, Cooper-Stanbury M, Donath S, Single E, Catalano P. Towards a standardised methodology for estimating alcohol-caused death, injury and illness in Australia. Aust N Z J Public Health. 2002. 26(5):443-50. doi:10.1111/j.1467-842x.2002.tb00345.x. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
30 | Christensen AI, Ekholm O, Gray L, Glumer C, Juel K. What is wrong with non-respondents? Alcohol-, drug- and smoking-related mortality and morbidity in a 12-year follow-up study of respondents and non-respondents in the Danish Health and Morbidity Survey. Addiction. 2015. 110(9):1505-12. doi:10.1111/add.12939. | Intervention/Exposure
31 | Cloud AJ, Thai A, Liao Y, Terry MB. The impact of cancer prevention guideline adherence on overall mortality in a high-risk cohort of women from the New York site of the Breast Cancer Family Registry. Breast Cancer Res Treat. 2015. 149(2):537-46. doi:10.1007/s10549-014-3234-x. | Intervention/Exposure; Outcome; Health Status
32 | Colpani V, Oppermann K, Spritzer PM. Causes of death and associated risk factors among climacteric women from Southern Brazil: a population based-study. BMC Public Health. 2014. 14:194. doi:10.1186/1471-2458-14-194. | Country
33 | Connor J, Kydd R, Shield K, Rehm J. The burden of disease and injury attributable to alcohol in New Zealanders under 80 years of age: marked disparities by ethnicity and sex. N Z Med J. 2015. 128(1409):15-28. | Study Design; Intervention/Exposure; Outcome
34 | Dai J, Mukamal KJ, Krasnow RE, Swan GE, Reed T. Higher usual alcohol consumption was associated with a lower 41-y mortality risk from coronary artery disease in men independent of genetic and common environmental factors: the prospective NHLBI Twin Study. Am J Clin Nutr. 2015. 102(1):31-9. doi:10.3945/ajcn.114.106435. | Sample size
35 | Daly M, Hall PA, Allan JL. Time Perspective and All-Cause Mortality: Evidence From the English Longitudinal Study of Ageing. Ann Behav Med. 2019. 53(5):486-492. doi:10.1093/abm/kay046. | Intervention/Exposure
36 | Davis JS, Banfield E, Lee HY, Peng HL, Chang S, Wood AC. Lifestyle behavior patterns and mortality among adults in the NHANES 1988-1994 population: A latent profile analysis. Prev Med. 2019. 120:131-139. doi:10.1016/j.ypmed.2019.01.012. | Intervention/Exposure
37 | Davletov K, McKee M, Berkinbayev S, Battakova Z, Vujnovic M, Rechel B. Regional differences in cardiovascular mortality in Kazakhstan: further evidence for the ‘Russian mortality paradox’?. Eur J Public Health. 2015. 25(5):890-4. doi:10.1093/eurpub/ckv019. | Outcome
38 | Dawson DA. Alcohol consumption, alcohol dependence, and all-cause mortality. Alcohol Clin Exp Res. 2000. 24(1):72-81. | Publication Date
39 | De la Torre R, Corella D, Castaner O, Martinez-Gonzalez MA, Salas-Salvado J, Vila J, Estruch R, Sorli JV, Aros F, Fiol M, Ros E, Serra-Majem L, Pinto X, Gomez-Gracia E, Lapetra J, Ruiz-Canela M, Basora J, Asensio EM, Covas MI, Fito M. Protective effect of homovanillyl alcohol on cardiovascular disease and total mortality: virgin olive oil, wine, and catechol-methylation. Am J Clin Nutr. 2017. 105(6):1297-1304. doi:10.3945/ajcn.116.145813. | Intervention/Exposure
40 | de Vegt F, Dekker JM, Groeneveld WJ, Nijpels G, Stehouwer CD, Bouter LM, Heine RJ. Moderate alcohol consumption is associated with lower risk for incident diabetes and mortality: the Hoorn Study. Diabetes Res Clin Pract. 2002. 57(1):53-60. doi:10.1016/s0168-8227(02)00013-x. | Publication Date
41 | Ding D, Rogers K, van der Ploeg H, Stamatakis E, Bauman AE. Traditional and Emerging Lifestyle Risk Behaviors and All-Cause Mortality in Middle-Aged and Older Adults: Evidence from a Large Population-Based Australian Cohort. PLoS Med. 2015. 12(12):e1001917. doi:10.1371/journal.pmed.1001917. | Comparator
42 | Doll R, Peto R, Boreham J, Sutherland I. Mortality in relation to alcohol consumption: a prospective study among male British doctors. Int J Epidemiol. 2005. 34(1):199-204. doi:10.1093/ije/dyh369. | Publication Date
43 | Doniec K, Stefler D, Murphy M, Gugushvili A, McKee M, Marmot M, Bobak M, King, L. Education and mortality in three Eastern European populations: findings from the PrivMort retrospective cohort study. Eur J Public Health. 2019. 29(3):549-554. doi:10.1093/eurpub/cky254. | Intervention/Exposure; Outcome
44 | Ebbert JO, Janney CA, Sellers TA, Folsom AR, Cerhan JR. The association of alcohol consumption with coronary heart disease mortality and cancer incidence varies by smoking history. J Gen Intern Med. 2005. 20(1):14-20. doi:10.1111/j.15251497.2005.40129.x. | Publication Date
45 | Egeberg A, Fowler JF, Jr, Gislason GH, Thyssen JP. Nationwide Assessment of Cause-Specific Mortality in Patients with Rosacea: A Cohort Study in Denmark. Am J Clin Dermatol. 2016. 17(6):673-679. doi:10.1007/s40257-016-0217-1. | Health Status
46 | Eguchi E, Iso H, Tanabe N, Wada Y, Yatsuya H, Kikuchi S, Inaba Y, Tamakoshi A. Healthy lifestyle behaviours and cardiovascular mortality among Japanese men and women: the Japan collaborative cohort study. Eur Heart J. 2012. 33(4):467-77. doi:10.1093/eurheartj/ehr429. | Outcome
47 | Eliasen M, Becker U, Gronbaek M, Juel K, Tolstrup JS. Alcohol-attributable and alcohol-preventable mortality in Denmark: an analysis of which intake levels contribute most to alcohol’s harmful and beneficial effects. Eur J Epidemiol. 2014. 29(1):15-26. doi:10.1007/s10654-013-9855-2. | Outcome
48 | Elovainio M, Hakulinen C, Pulkki-Raback L, Virtanen M, Josefsson K, Jokela M, Vahtera J, Kivimaki M. Contribution of risk factors to excess mortality in isolated and lonely individuals: an analysis of data from the UK Biobank cohort study. Lancet Public Health. 2017. 2(6):e260-e266. doi:10.1016/s2468-2667(17)30075-0. | Intervention/Exposure
49 | Emberson JR, Shaper AG, Wannamethee SG, Morris RW, Whincup PH. Alcohol intake in middle age and risk of cardiovascular disease and mortality: accounting for intake variation over time. Am J Epidemiol. 2005. 161(9):856-63. doi:10.1093/aje/kwi111. | Publication Date
50 | Eyawo O, McGinnis KA, Justice AC, Fiellin DA, Hahn JA, Williams EC, Gordon AJ, Marshall BDL, Kraemer KL, Crystal S, Gaither JR, Edelman EJ, Bryant KJ, Tate JP. Alcohol and Mortality: Combining Self-Reported (AUDIT-C) and Biomarker Detected (PEth) Alcohol Measures Among HIV Infected and Uninfected. Journal of acquired immune deficiency syndromes (1999). 2018. 77(2):135-143. doi:10.1097/QAI.0000000000001588. | Sample size
51 | Farchi G, Fidanza F, Giampaoli S, Mariotti S, Menotti A. Alcohol and survival in the Italian rural cohorts of the Seven Countries Study. Int J Epidemiol. 2000. 29(4):667-71. doi:10.1093/ije/29.4.667. | Publication Date
52 | Fichter MM, Quadflieg N, Fischer UC. Severity of alcohol-related problems and mortality: results from a 20-year prospective epidemiological community study. Eur Arch Psychiatry Clin Neurosci. 2011. 261(4):293-302. doi:10.1007/s00406-010-0141-y. | Intervention/Exposure
53 | Fillmore KM, Kerr WC, Bostrom A. Changes in drinking status, serious illness and mortality. J Stud Alcohol. 2003. 64(2):278-85. doi:10.15288/jsa.2003.64.278. | Publication Date
54 | Ford ES, Zhao G, Tsai J, Li C. Low-risk lifestyle behaviors and all-cause mortality: findings from the National Health and Nutrition Examination Survey III Mortality Study. Am J Public Health. 2011. 101(10):1922-9. doi:10.2105//ajph.2011.300167 10.2105/ajph.2011.300167. | Comparator
55 | Freiberg MS, Chang YF, Kraemer KL, Robinson JG, Adams-Campbell LL, Kuller LL. Alcohol consumption, hypertension, and total mortality among women. Am J Hypertens. 2009. 22(11):1212-8. doi:10.1038/ajh.2009.172. | Publication Date
56 | Friesema IH, Zwietering PJ, Veenstra MY, Knottnerus JA, Garretsen HF, Kester AD, Lemmens PH. The effect of alcohol intake on cardiovascular disease and mortality disappeared after taking lifetime drinking and covariates into account. Alcohol Clin Exp Res. 2008. 32(4):645-51. doi:10.1111/j.1530-0277.2007.00612.x. | Publication Date
57 | Friesema IH, Zwietering PJ, Veenstra MY, Knottnerus JA, Garretsen HF, Lemmens PH. Alcohol intake and cardiovascular disease and mortality: the role of pre-existing disease. J Epidemiol Community Health. 2007. 61(5):441-6. doi:10.1136/jech.2006.050419. | Publication Date
58 | Furuya H, Young AF, Powers JR, Byles JE. Alcohol consumption and physical health-related quality of life in older women using the transformation of SF-36 to account for death. Nihon Arukoru Yakubutsu Igakkai Zasshi. 2008. 43(2):97-109. | Outcome
59 | Gargiulo G, Testa G, Cacciatore F, Mazzella F, Galizia G, Della-Morte D, Langellotto A, Pirozzi G, Ferro G, Ferrara N, Rengo F, Abete P. Moderate alcohol consumption predicts long-term mortality in elderly subjects with chronic heart failure. J Nutr Health Aging. 2013. 17(5):480-5. doi:10.1007/s12603-012-0430-4. | Comparator; Health Status
60 | Gaziano JM, Gaziano TA, Glynn RJ, Sesso HD, Ajani UA, Stampfer MJ, Manson JE, Hennekens CH, Buring JE. Light-to-moderate alcohol consumption and mortality in the Physicians’ Health Study enrollment cohort. J Am Coll Cardiol. 2000. 35(1):96-105. doi:10.1016/s0735-1097(99)00531-8. | Publication Date
61 | Glover J, Gold, JA. Alcohol Use Increasing Among Adults 65 and Older. Wmj. 2017. 116(3):182-183. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
62 | Golden, RN, Maroney, L. Addressing a deadly epidemic. Wmj. 2009. 108(7):377-8. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
63 | Gray, CM, Carroll, RJ, Lentjes, MAH, Keogh, RH. Correcting for measurement error in fractional polynomial models using Bayesian modelling and regression calibration, with an application to alcohol and mortality. Biom J. 2019. 61(3):558-573. doi:10.1002/bimj.201700279. | Outcome
64 | Greenfield, TK, Rehm J, Rogers, JD. Effects of depression and social integration on the relationship between alcohol consumption and all-cause mortality. Addiction. 2002. 97(1):29-38. doi:10.1046/j.1360-0443.2002.00065.x. | Publication Date
65 | Greenlee H, Strizich G, Lovasi, GS, Kaplan, RC, Biggs, ML, Li, CI, Richardson J, Burke, GL, Fitzpatrick, AL, Fretts, AM, Psaty, BM, Fried, LP. Concordance With Prevention Guidelines and Subsequent Cancer, Cardiovascular Disease, and Mortality: A Longitudinal Study of Older Adults. Am J Epidemiol. 2017. 186(10):1168-1179. doi:10.1093/aje/kwx150. | Intervention/Exposure
66 | Gronbaek M, Becker U, Johansen D, Gottschau A, Schnohr P, Hein, HO, Jensen G, Sorensen, TI. Type of alcohol consumed and mortality from all causes, coronary heart disease, and cancer. Ann Intern Med. 2000. 133(6):411-9. doi:10.7326/0003-4819-133-6-200009190-00008. | Publication Date
67 | Gronbaek M, Johansen D, Becker U, Hein, HO, Schnohr P, Jensen G, Vestbo J, Sorensen, TI. Changes in alcohol intake and mortality: a longitudinal population-based study. Epidemiology. 2004. 15(2):222-8. doi:10.1097/01.ede.0000112219.01955.56. | Publication Date
68 | Gun, RT, Pratt N, Ryan P, Gordon I, Roder, D. Tobacco and alcohol-related mortality in men: estimates from the Australian cohort of petroleum industry workers. Aust N Z J Public Health. 2006. 30(4):318-24. doi:10.1111/j.1467-842x.2006.tb00842.x. | Publication Date
69 | Hallgren, MA, Hogberg P, Andreasson, S. Alcohol consumption and harm among elderly Europeans: falling between the cracks. Eur J Public Health. 2010. 20(6):616-7. doi:10.1093/eurpub/ckq111. | Study Design
70 | Halme, JT, Seppa K, Alho H, Poikolainen K, Pirkola S, Aalto, M. Alcohol consumption and all-cause mortality among elderly in Finland. Drug Alcohol Depend. 2010. 106(2-3):212-8. doi:10.1016/j.drugalcdep.2009.08.017. | Comparator
71 | Hamer M, O’Donovan G, Stamatakis, E. Lifestyle risk factors, obesity and infectious disease mortality in the general population: Linkage study of 97,844 adults from England and Scotland. Prev Med. 2019. 123:65-70. doi:10.1016/j.ypmed.2019.03.002. | Outcome
72 | Harriss, LR, English, DR, Hopper, JL, Powles J, Simpson, JA, O’Dea K, Giles, GG, Tonkin, AM. Alcohol consumption and cardiovascular mortality accounting for possible misclassification of intake: 11-year follow-up of the Melbourne Collaborative Cohort Study. Addiction. 2007. 102(10):1574-85. doi:10.1111/j.1360-0443.2007.01947.x. | Outcome
73 | Hart, CL, Davey Smith G, Gruer L, Watt, GC. The combined effect of smoking tobacco and drinking alcohol on cause-specific mortality: a 30 year cohort study. BMC Public Health. 2010. 10:789. doi:10.1186/1471-2458-10-789. | Comparator
74 | Hart CL, Smith GD. Alcohol consumption and mortality and hospital admissions in men from the Midspan collaborative cohort study. Addiction. 2008. 103(12):1979-86. doi:10.1111/j.1360-0443.2008.02373.x. | Publication Date
75 | Haupt TH, Rasmussen LJH, Kallemose T, Ladelund S, Andersen O, Pisinger C, Eugen-Olsen J. Healthy lifestyles reduce suPAR and mortality in a Danish general population study. Immun Ageing. 2019. 16:1. doi:10.1186/s12979-018-0141-8. | Intervention/Exposure; Outcome; Health Status
76 | Hayward RD, Krause, N. The effect of belonging to an alcohol-proscribing religious group on the relationship between moderate alcohol consumption and mortality. Soc Sci Med. 2014. 101:1-8. doi:10.1016/j.socscimed.2013.10.039. | Comparator
77 | Heitz AE, Baumgartner RN, Baumgartner KB, Boone SD. Healthy lifestyle impact on breast cancer-specific and all-cause mortality. Breast Cancer Res Treat. 2018. 167(1):171-181. doi:10.1007/s10549-017-4467-2. | Health Status
78 | Henry JA, Moloney C, Rivas C, Goldin RD. Increase in alcohol related deaths: is hepatitis C a factor?. J Clin Pathol. 2002. 55(9):704-7. doi:10.1136/jcp.55.9.704. | Intervention/Exposure; Outcome
79 | Hernandez-Hernandez A, Gea A, Ruiz-Canela M, Toledo E, Beunza JJ, Bes-Rastrollo M, Martinez-Gonzalez MA. Mediterranean Alcohol-Drinking Pattern and the Incidence of Cardiovascular Disease and Cardiovascular Mortality: The SUN Project. Nutrients. 2015. 7(11):9116-26. doi:10.3390/nu7115456. | Outcome
80 | Hernández-Vásquez A, Vargas-Fernández R, Rebatta-Acuña A, Bendezu-Quispe, G. Trends in mortality due to gastrointestinal diseases attributed to alcohol use in Peru from 2003 to 2016. Revista de gastroenterologia del Peru : organo oficial de la Sociedad de Gastroenterologia del Peru. 2019. 39(3):239-245. | Intervention/Exposure; Outcome
81 | Heroux M, Janssen I, Lam M, Lee, DC, Hebert, JR, Sui X, Blair, SN. Dietary patterns and the risk of mortality: impact of cardiorespiratory fitness. Int J Epidemiol. 2010. 39(1):197-209. doi:10.1093/ije/dyp191. | Intervention/Exposure
82 | Hoiseth G, Magnus P, Knudsen GP, Jansen MD, Naess O, Tambs K, Morland J. Is ADH1C genotype relevant for the cardioprotective effect of alcohol? Alcohol. 2013. 47(2):81-4. doi:10.1016/j.alcohol.2012.12.005. | Outcome
83 | Holahan CJ, Brennan PL, Schutte KK, Holahan CK, Hixon JG, Moos RH. Drinking Level Versus Drinking Pattern and Cigarette Smoking Among Older Adults. Alcohol Clin Exp Res. 2018. 42(4):795-802. doi:10.1111/acer.13607. | Sample size
84 | Holahan CJ, Schutte KK, Brennan PL, Holahan CK, Moos RH. Episodic heavy drinking and 20-year total mortality among late-life moderate drinkers. Alcohol Clin Exp Res. 2014. 38(5):1432-8. doi:10.1111/acer.12381. | Sample size
85 | Holahan CJ, Schutte KK, Brennan PL, North RJ, Holahan CK, Moos BS, Moos RH. Wine consumption and 20-year mortality among late-life moderate drinkers. J Stud Alcohol Drugs. 2012. 73(1):80-8. doi:10.15288/jsad.2012.73.80. | Sample size
86 | Howie EK, Sui X, Lee DC, Hooker SP, Hebert JR, Blair SN. Alcohol consumption and risk of all-cause and cardiovascular disease mortality in men. J Aging Res. 2011. 2011:805062. doi:10.4061/2011/805062. | Comparator
87 | Hulsegge G, Looman M, Smit HA, Daviglus ML, van der Schouw YT, Verschuren WM. Lifestyle Changes in Young Adulthood and Middle Age and Risk of Cardiovascular Disease and All-Cause Mortality: The Doetinchem Cohort Study. J Am Heart Assoc. 2016. 5(1). doi:10.1161/jaha.115.002432. | Comparator
88 | Huynh QL, Reid CM, Chowdhury EK, Huq MM, Billah B, Wing LM, Tonkin AM, Simons LA, Nelson MR. Prediction of cardiovascular and all-cause mortality at 10 years in the hypertensive aged population. Am J Hypertens. 2015. 28(5):649-56. doi:10.1093/ajh/hpu213. | Intervention/Exposure; Health Status
89 | Ikehara S, Iso H, Toyoshima H, Date C, Yamamoto A, Kikuchi S, Kondo T, Watanabe Y, Koizumi A, Wada Y, Inaba Y, Tamakoshi A. Alcohol consumption and mortality from stroke and coronary heart disease among Japanese men and women: the Japan collaborative cohort study. Stroke. 2008. 39(11):2936-42. doi:10.1161/strokeaha.108.520288. | Outcome
90 | Im PK, Millwood IY, Chen Y, Guo Y, Du H, Kartsonaki C, Bian Z, Tan Y, Su J, Li Y, Yu C, Lv J, Li L, Yang L, Chen Z. Problem drinking, wellbeing and mortality risk in Chinese men: findings from the China Kadoorie Biobank. Addiction. 2019. doi:10.1111/add.14873. | Country
91 | Ivey KL, Hodgson JM, Croft KD, Lewis JR, Prince RL. Flavonoid intake and all-cause mortality. Am J Clin Nutr. 2015. 101(5):1012-20. doi:10.3945/ajcn.113.073106. | Intervention/Exposure
92 | Ivey KL, Jensen MK, Hodgson JM, Eliassen AH, Cassidy A, Rimm EB. Association of flavonoid-rich foods and flavonoids with risk of all-cause mortality. Br J Nutr. 2017. 117(10):1470-1477. doi:10.1017/s0007114517001325. | Intervention/Exposure
93 | Jakovljevic B, Stojanov V, Paunovic K, Belojevic G, Milic N. Alcohol consumption and mortality in Serbia: twenty-year follow-up study. Croat Med J. 2004. 45(6):764-8. | Publication Date
94 | Jankovic N, Geelen A, Streppel MT, de Groot LC, Kiefte-de Jong JC, Orfanos P, Bamia C, Trichopoulou A, Boffetta P, Bobak M, Pikhart H, Kee F, O’Doherty MG, Buckland G, Woodside J, Franco OH, Ikram MA, Struijk EA, Pajak A, Malyutina S, Kubinova R, Wennberg M, Park Y, Bueno-de-Mesquita HB, Kampman E, Feskens EJ. WHO guidelines for a healthy diet and mortality from cardiovascular disease in European and American elderly: the CHANCES project. Am J Clin Nutr. 2015. 102(4):745-56. doi:10.3945/ajcn.114.095117. | Outcome
95 | Jayanama K, Theou O, Blodgett JM, Cahill L, Rockwood K. Frailty, nutrition-related parameters, and mortality across the adult age spectrum. BMC Med. 2018. 16(1):188. doi:10.1186/s12916-018-1176-6. | Intervention/Exposure; Outcome
96 | Jeong HG, Kim TH, Lee JJ, Lee SB, Park JH, Huh Y, Chin HJ, Jhoo JH, Lee DY, Woo JI, Kim KW. Impact of alcohol use on mortality in the elderly: results from the Korean Longitudinal Study on Health and Aging. Drug Alcohol Depend. 2012. 121(1-2):133-9. doi:10.1016/j.drugalcdep.2011.08.017. | Sample size
97 | Jiang H, Livingston M, Room R, Gan Y, English D, Chenhall R. Can public health policies on alcohol and tobacco reduce a cancer epidemic? Australia’s experience. BMC Med. 2019. 17(1):213. doi:10.1186/s12916-019-1453-z. | Intervention/Exposure; Outcome
98 | Johansen D, Gronbaek M, Overvad K, Schnohr P, Andersen PK. Generalized additive models applied to analysis of the relation between amount and type of alcohol and all-cause mortality. Eur J Epidemiol. 2005. 20(1):29-36. doi:10.1007/s10654-004-2172-z. | Comparator
99 | Johnson JE, Finney JW, Moos RH. Predictors of 5-year mortality following inpatient/residential group treatment for substance use disorders. Addict Behav. 2005. 30(7):1300-16. doi:10.1016/j.addbeh.2005.01.005. | Intervention/Exposure; Health Status
100 | Kamsa-ard S, Promthet S, Lewington S, Burrett JA, Sherliker P, Kamsa-ard S, Suwanrungruang K, Parkin DM. Alcohol consumption and mortality: the Khon Kaen Cohort Study, Thailand. J Epidemiol. 2014. 24(2):154-60. doi:10.2188/jea.je20130092. | Country
101 | Katcher BS, Reiter RB, Aragon TJ. Estimating alcohol-related premature mortality in San Francisco: use of population-attributable fractions from the global burden of disease study. BMC Public Health. 2010. 10:682. doi:10.1186/1471-2458-10-682. | Comparator; Outcome
102 | Kerr WC, Fillmore KM, Marvy P. Beverage-specific alcohol consumption and cirrhosis mortality in a group of English-speaking beer-drinking countries. Addiction. 2000. 95(3):339-46. doi:10.1046/j.1360-0443.2000.9533394.x. | Outcome
103 | Keys A, Menott A, Karvonen, MJ, Aravanjs C, Blackburn H, Buzina R, Djordjevic, BS, Dontas, AS, Fidanza F, Keys, MH, Kromhout D, Nedeljkovic S, Punsar S, Seccareccia F, Toshima, H. The diet and 15-year death rate in the seven countries study. American Journal of Epidemiology. 2017. 185(11):1130-1142. doi:10.1093/aje/kwx101. | Publication Date
104 | Khang, YH, Lynch, JW, Yang S, Harper S, Yun, SC, Jung-Choi K, Kim, HR. The contribution of material, psychosocial, and behavioral factors in explaining educational and occupational mortality inequalities in a nationally representative sample of South Koreans: relative and absolute perspectives. Soc Sci Med. 2009. 68(5):858-66. doi:10.1016/j.socscimed.2008.12.003. | Publication Date
105 | Khaw, KT, Wareham N, Bingham S, Welch A, Luben R, Day, N. Combined impact of health behaviours and mortality in men and women: the EPIC-Norfolk prospective population study. PLoS Med. 2008. 5(1):e12. doi:10.1371/journal.pmed.0050012. | Publication Date
106 | Kiiskinen T, Mars, NJ, Palviainen T, Koskela J, Ramo, JT, Ripatti P, Ruotsalainen S, Palotie A, Madden, PAF, Rose, RJ, Kaprio J, Salomaa V, Makela P, Havulinna, AS, Ripatti, S. Genomic prediction of alcohol-related morbidity and mortality. Transl Psychiatry. 2020. 10(1):23. doi:10.1038/s41398-019-0676-2. | Intervention/exposure
107 | Kim, MK, Ko, MJ, Han, JT. Alcohol consumption and mortality from all-cause and cancers among 1.34 million Koreans: the results from the Korea national health insurance corporation’s health examinee cohort in 2000. Cancer Causes Control. 2010. 21(12):2295-302. doi:10.1007/s10552-010-9656-9. | Comparator
108 | Kinder, LS, Bryson, CL, Sun H, Williams, EC, Bradley, KA. Alcohol screening scores and all-cause mortality in male Veterans Affairs patients. J Stud Alcohol Drugs. 2009. 70(2):253-60. doi:10.15288/jsad.2009.70.253. | Comparator
109 | King, DE, Mainous, AG, 3rd, Geesey, ME. Adopting moderate alcohol consumption in middle age: subsequent cardiovascular events. Am J Med. 2008. 121(3):201-6. doi:10.1016/j.amjmed.2007.12.004. | Outcome
110 | King, DE, Mainous, AG, 3rd, Matheson, EM, Everett, CJ. Impact of healthy lifestyle on mortality in people with normal blood pressure, LDL cholesterol, and C-reactive protein. Eur J Prev Cardiol. 2013. 20(1):73-9. doi:10.1177/1741826711425776. | Intervention/Exposure
111 | Klatsky, AL, Friedman, GD, Armstrong, MA, Kipp, H. Wine, liquor, beer, and mortality. Am J Epidemiol. 2003. 158(6):585-95. doi:10.1093/aje/kwg184. | Publication Date
112 | Klatsky, AL, Udaltsova, N. Alcohol Drinking and Total Mortality Risk. Annals of Epidemiology. 2007. 17(5 SUPPL.):S63-S67. doi:10.1016/j.annepidem.2007.01.014. | Publication Date
113 | Knoops, KT, de Groot, LC, Kromhout D, Perrin, AE, Moreiras-Varela O, Menotti A, van Staveren, WA. Mediterranean diet, lifestyle factors, and 10-year mortality in elderly European men and women: the HALE project. Jama. 2004. 292(12):1433-9. doi:10.1001/jama.292.12.1433. | Publication Date
114 | Koch, MB, Diderichsen F, Gronbaek M, Juel, K. What is the association of smoking and alcohol use with the increase in social inequality in mortality in Denmark? A nationwide register-based study. BMJ Open. 2015. 5(5):e006588. doi:10.1136/bmjopen-2014-006588. | Intervention/Exposure; Outcome
115 | Kontro, TK, Sarna S, Kaprio J, Kujala, UM. Mortality and health-related habits in 900 Finnish former elite athletes and their brothers. Br J Sports Med. 2018. 52(2):89-95. doi:10.1136/bjsports-2017-098206. | Intervention/Exposure; Comparator
116 | Korotayev A, Khaltourina D, Meshcherina K, Zamiatnina, E. Distilled Spirits Overconsumption as the Most Important Factor of Excessive Adult Male Mortality in Europe. Alcohol Alcohol. 2018. 53(6):742-752. doi:10.1093/alcalc/agy054. | Intervention/Exposure
117 | Kovše K, Tomšič S, Ponikvar, BM, Nadrag, P. Alcohol related harm in Slovenia. Zdravniski Vestnik. 2012. 81(2):119-127. | Language
118 | Kristenson H, Osterling A, Nilsson, JA, Lindgarde, F. Prevention of alcohol-related deaths in middle-aged heavy drinkers. Alcohol Clin Exp Res. 2002. 26(4):478-84. doi:10.1111/j.1530-0277.2002.tb02564.x. | Intervention/Exposure; Outcome
119 | Krokstad S, Ding D, Grunseit, AC, Sund, ER, Holmen, TL, Rangul V, Bauman, A. Multiple lifestyle behaviours and mortality, findings from a large population-based Norwegian cohort study - The HUNT Study. BMC Public Health. 2017. 17(1):58. doi:10.1186/s12889-016-3993-x. | Intervention/Exposure
120 | Krueger, PM, Saint Onge, JM, Chang, VW. Race/ethnic differences in adult mortality: the role of perceived stress and health behaviors. Soc Sci Med. 2011. 73(9):1312-22. doi:10.1016/j.socscimed.2011.08.007. | Comparator
121 | Kvaavik E, Batty, GD, Ursin G, Huxley R, Gale, CR. Influence of individual and combined health behaviors on total and cause-specific mortality in men and women: the United Kingdom health and lifestyle survey. Arch Intern Med. 2010. 170(8):711-8. doi:10.1001/archinternmed.2010.76. | Comparator
122 | Laaksonen M, Talala K, Martelin T, Rahkonen O, Roos E, Helakorpi S, Laatikainen T, Prattala, R. Health behaviours as explanations for educational level differences in cardiovascular and all-cause mortality: a follow-up of 60 000 men and women over 23 years. Eur J Public Health. 2008. 18(1):38-43. doi:10.1093/eurpub/ckm051. | Publication Date
123 | Laatikainen T, Manninen L, Poikolainen K, Vartiainen, E. Increased mortality related to heavy alcohol intake pattern. J Epidemiol Community Health. 2003. 57(5):379-84. doi:10.1136/jech.57.5.379. | Publication Date
124 | Laine, JE, Baltar, VT, Stringini S, Gandini M, Chadeau-Hyam M, Kivimaki M, Severi G, Perduca V, Hodge, AM, Dugue, PA, Giles, GG, Milne, RL, Barros H, Sacerdote C, Krogh V, Panico S, Tumino R, Goldberg M, Zins M, Delpierre C, Vineis, P. Reducing socio-economic inequalities in all-cause mortality: a counterfactual mediation approach. Int J Epidemiol. 2019. doi:10.1093/ije/dyz248. | Intervention/Exposure
125 | Lang I, Guralnik J, Wallace, RB, Melzer, D. What level of alcohol consumption is hazardous for older people? Functioning and mortality in U.S. and English national cohorts. J Am Geriatr Soc. 2007. 55(1):49-57. doi:10.1111/j.1532-5415.2006.01007.x. | Publication Date
126 | Lapidus L, Bengtsson C, Bergfors E, Bjorkelund C, Spak F, Lissner, L. Alcohol intake among women and its relationship to diabetes incidence and all-cause mortality: the 32-year follow-up of a population study of women in Gothenburg, Sweden. Diabetes Care. 2005. 28(9):2230-5. doi:10.2337/diacare.28.9.2230. | Publication Date
127 | Laranjeira E, Szrek, H. Going beyond life expectancy in assessments of health systems’ performance: life expectancy adjusted by perceived health status. Int J Health Econ Manag. 2016. 16(2):133-161. doi:10.1007/s10754-015-9183-z. | Study Design
128 | Larsson, SC, Kaluza J, Wolk, A. Combined impact of healthy lifestyle factors on lifespan: two prospective cohorts. J Intern Med. 2017. 282(3):209-219. doi:10.1111/joim.12637. | Intervention/Exposure; Comparator
129 | Lee, DH, Folsom, AR, Jacobs, DR, Jr. Iron, zinc, and alcohol consumption and mortality from cardiovascular diseases: the Iowa Women’s Health Study. Am J Clin Nutr. 2005. 81(4):787-91. doi:10.1093/ajcn/81.4.787. | Outcome
130 | Lee I, Kim S, Kang, H. Lifestyle Risk Factors and All-Cause and Cardiovascular Disease Mortality: Data from the Korean Longitudinal Study of Aging. Int J Environ Res Public Health. 2019. 16(17). doi:10.3390/ijerph16173040. | Comparator
131 | Lee, JH, Lee, DH. Comparison of injury pattern and clinical outcomes between young adults and elderly patients with alcohol-related injury in South Korea 2011-2016. PeerJ. 2019. 7:e7704. doi:10.7717/peerj.7704. | Intervention/Exposure; Health Status
132 | Lee, SJ, Sudore, RL, Williams, BA, Lindquist K, Chen, HL, Covinsky, KE. Functional limitations, socioeconomic status, and allcause mortality in moderate alcohol drinkers. J Am Geriatr Soc. 2009. 57(6):955-62. doi:10.1111/j.1532-5415.2009.02184.x. | Publication Date
133 | Levantesi G, Marfisi R, Mozaffarian D, Franzosi, MG, Maggioni A, Nicolosi, GL, Schweiger C, Silletta M, Tavazzi L, Tognoni G, Marchioli R. Wine consumption and risk of cardiovascular events after myocardial infarction: results from the GISSI-Prevenzione trial. Int J Cardiol. 2013. 163(3):282-287. doi:10.1016/j.ijcard.2011.06.053. | Health Status
134 | Lhachimi SK, Nusselder WJ, Smit HA, Baili P, Bennett K, Fernandez E, Kulik MC, Lobstein T, Pomerleau J, Boshuizen HC, Mackenbach JP. Potential health gains and health losses in eleven EU countries attainable through feasible prevalences of the life-style related risk factors alcohol, BMI, and smoking: a quantitative health impact assessment. BMC Public Health. 2016. 16:734. doi:10.1186/s12889-016-3299-z. | Study Design; Outcome
135 | Liao Y, McGee, DL, Cao G, Cooper RS. Alcohol intake and mortality: findings from the National Health Interview Surveys (1988 and 1990). Am J Epidemiol. 2000. 151(7):651-9. doi:10.1093/oxfordjournals.aje.a010259. | Publication Date
136 | Lin Y, Kikuchi S, Tamakoshi A, Wakai K, Kawamura T, Iso H, Ogimoto I, Yagyu K, Obata Y, Ishibashi T. Alcohol consumption and mortality among middle-aged and elderly Japanese men and women. Ann Epidemiol. 2005. 15(8):590-7. doi:10.1016/j.annepidem.2004.10.010. | Publication Date
137 | Makela P, Paljarvi T, Poikolainen K. Heavy and nonheavy drinking occasions, all-cause and cardiovascular mortality and hospitalizations: a follow-up study in a population with a low consumption level. J Stud Alcohol. 2005. 66(6):722-8. doi:10.15288/jsa.2005.66.722. | Comparator
138 | Malinski MK, Sesso HD, Lopez-Jimenez F, Buring JE, Gaziano JM. Alcohol consumption and cardiovascular disease mortality in hypertensive men. Arch Intern Med. 2004. 164(6):623-8. doi:10.1001/archinte.164.6.623. | Publication Date
139 | Malyutina S, Bobak M, Kurilovitch S, Gafarov V, Simonova G, Nikitin Y, Marmot M. Relation between heavy and binge drinking and all-cause and cardiovascular mortality in Novosibirsk, Russia: a prospective cohort study. Lancet. 2002. 360(9344):1448-54. doi:10.1016/s0140-6736(02)11470-x. | Publication Date
140 | Manuel DG, Perez R, Sanmartin C, Taljaard M, Hennessy D, Wilson K, Tanuseputro P, Manson H, Bennett C, Tuna M, Fisher S, Rosella LC. Measuring Burden of Unhealthy Behaviours Using a Multivariable Predictive Approach: Life Expectancy Lost in Canada Attributable to Smoking, Alcohol, Physical Inactivity, and Diet. PLoS Med. 2016. 13(8):e1002082. doi:10.1371/journal.pmed.1002082. | Comparator
141 | Maraldi C, Volpato S, Kritchevsky SB, Cesari M, Andresen E, Leeuwenburgh C, Harris TB, Newman AB, Kanaya A, Johnson KC, Rodondi N, Pahor M. Impact of inflammation on the relationship among alcohol consumption, mortality, and cardiac events: the health, aging, and body composition study. Arch Intern Med. 2006. 166(14):1490-7. doi:10.1001/archinte.166.14.1490. | Publication Date
142 | Marteau TM, White M, Rutter H, Petticrew M, Mytton OT, McGowan JG, Aldridge RW. Increasing healthy life expectancy equitably in England by 5 years by 2035: could it be achieved?. Lancet. 2019. 393(10191):2571-2573. doi:10.1016/s0140-6736(19)31510-7. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
143 | Martikainen P, Makela P, Peltonen R, Myrskyla M. Income differences in life expectancy: the changing contribution of harmful consumption of alcohol and smoking. Epidemiology. 2014. 25(2):182-90. doi:10.1097/ede.0000000000000064. | Intervention/Exposure; Outcome
144 | Martin J, Barry J, Goggin D, Morgan K, Ward M, O’Suilleabhain T. Alcohol-attributable mortality in Ireland. Alcohol Alcohol. 2010. 45(4):379-86. doi:10.1093/alcalc/agq032. | Intervention/Exposure; Outcome
145 | Martin-Diener E, Meyer J, Braun J, Tarnutzer S, Faeh D, Rohrmann S, Martin BW. The combined effect on survival of four main behavioural risk factors for non-communicable diseases. Prev Med. 2014. 65:148-52. doi:10.1016/j.ypmed.2014.05.023. | Comparator
146 | Marugame T, Yamamoto S, Yoshimi I, Sobue T, Inoue M, Tsugane S. Patterns of alcohol drinking and all-cause mortality: results from a large-scale population-based cohort study in Japan. Am J Epidemiol. 2007. 165(9):1039-46. doi:10.1093/aje/kwk112. | Publication Date
147 | McCartney DL, Hillary RF, Stevenson AJ, Ritchie SJ, Walker RM, Zhang Q, Morris SW, Bermingham ML, Campbell A, Murray AD, Whalley HC, Gale CR, Porteous DJ, Haley CS, McRae AF, Wray NR, Visscher PM, McIntosh AM, Evans KL, Deary IJ, Marioni RE. Epigenetic prediction of complex traits and death. Genome Biol. 2018. 19(1):136. doi:10.1186/s13059-018-1514-1. | Intervention/Exposure; Outcome
148 | McCartney G, Shipley M, Hart C, Davey-Smith G, Kivimäki M, Walsh D, Watt GC, Batty GD. Why do males in Scotland die younger than those in England? evidence from three prospective cohort studies. PLoS ONE. 2012. 7(7). doi:10.1371/journal.pone.0038860. | Study Design; Intervention/Exposure
149 | McCaul KA, Almeida OP, Hankey GJ, Jamrozik K, Byles JE, Flicker L. Alcohol use and mortality in older men and women. Addiction. 2010. 105(8):1391-400. doi:10.1111/j.1360-0443.2010.02972.x. | Comparator
150 | Mehta NK, House JS, Elliott MR. Dynamics of health behaviours and socioeconomic differences in mortality in the USA. J Epidemiol Community Health. 2015. 69(5):416-22. doi:10.1136/jech-2014-204248. | Intervention/Exposure
151 | Melo APS, Franca EB, Malta DC, Garcia LP, Mooney M, Naghavi M. Mortality due to cirrhosis, liver cancer, and disorders attributed to alcohol use: Global Burden of Disease in Brazil, 1990 and 2015. Rev Bras Epidemiol. 2017. 20Suppl 01(Suppl 01):61-74. doi:10.1590/1980-5497201700050006. | Outcome
152 | Meyer J, Doring A, Herder C, Roden M, Koenig W, Thorand B. Dietary patterns, subclinical inflammation, incident coronary heart disease and mortality in middle-aged men from the MONICA/KORA Augsburg cohort study. Eur J Clin Nutr. 2011. 65(7):800-7. doi:10.1038/ejcn.2011.37. | Intervention/Exposure
153 | Mills JA, Beach, SRH, Dogan M, Simons, RL, Gibbons, FX, Long, JD, Philibert, R. A Direct Comparison of the Relationship of Epigenetic Aging and Epigenetic Substance Consumption Markers to Mortality in the Framingham Heart Study. Genes (Basel). 2019. 10(1). doi:10.3390/genes10010051. | Intervention/Exposure
154 | Millwood IY, Walters RG, Mei XW, Guo Y, Yang L, Bian Z, Bennett DA, Chen Y, Dong C, Hu R, Zhou G, Yu B, Jia W, Parish S, Clarke R, Davey Smith G, Collins R, Holmes MV, Li L, Peto R, Chen, Z. Conventional and genetic evidence on alcohol and vascular disease aetiology: a prospective study of 500 000 men and women in China. Lancet. 2019. 393(10183):1831-1842. doi:10.1016/s0140-6736(18)31772-0. | Country
155 | Mink PJ, Scrafford CG, Barraj LM, Harnack L, Hong CP, Nettleton JA, Jacobs, DR, Jr. Flavonoid intake and cardiovascular disease mortality: a prospective study in postmenopausal women. Am J Clin Nutr. 2007. 85(3):895-909. doi:10.1093/ajcn/85.3.895. | Outcome
156 | Miyazaki M, Une H. Japanese alcoholic beverage and all cause mortality in Japanese adult men. J Epidemiol. 2001. 11(5):219-23. doi:10.2188/jea.11.219. | Publication Date
157 | Moore AA, Giuli L, Gould R, Hu P, Zhou K, Reuben D, Greendale G, Karlamangla A. Alcohol use, comorbidity, and mortality. J Am Geriatr Soc. 2006. 54(5):757-62. doi:10.1111/j.1532-5415.2006.00728.x. | Publication Date
158 | Morc, LS, Johansen D, Lokkegaard E, Hundrup YA, Gronbaek M. Drinking pattern and mortality in Danish nurses. Eur J Clin Nutr. 2008. 62(6):817-22. doi:10.1038/sj.ejcn.1602799. | Publication Date
159 | Mukamal KJ, Chen CM, Rao SR, Breslow RA. Alcohol consumption and cardiovascular mortality among U.S. adults, 1987 to 2002. J Am Coll Cardiol. 2010. 55(13):1328-35. doi:10.1016/j.jacc.2009.10.056. | Outcome
160 | Murray RP, Connett JE, Tyas SL, Bond R, Ekuma O, Silversides CK, Barnes GE. Alcohol volume, drinking pattern, and cardiovascular disease morbidity and mortality: is there a U-shaped function?. Am J Epidemiol. 2002. 155(3):242-8. doi:10.1093/aje/155.3.242. | Outcome
161 | Muscari A, Bianchi G, Conte C, Forti P, Magalotti D, Pandolfi P, Vaccheri A, Zoli M. No Direct Survival Effect of Light to Moderate Alcohol Drinking in Community-Dwelling Older Adults. J Am Geriatr Soc. 2015. 63(12):2526-2533. doi:10.1111/jgs.13837. | Comparator
162 | Nagy J, Sipka S, SipkaJr S, Kocsis J, Horvath Z. The Hardness of Drinking Water Negatively while Socio-Economic Deprivation Positively Correlate with the Age-Adjusted Mortality Rates due to Cardiovascular Diseases in Hungarian Wine Regions. Int J Environ Res Public Health. 2019. 16(18). doi:10.3390/ijerph16183437. | Intervention/Exposure; Outcome
163 | Naimi TS, Xuan Z, Brown DW, Saitz R. Confounding and studies of ‘moderate’ alcohol consumption: the case of drinking frequency and implications for low-risk drinking guidelines. Addiction. 2013. 108(9):1534-43. doi:10.1111/j.1360-0443.2012.04074.x. | Outcome
164 | Nakamura Y, Ueshima H, Kadota A, Hozawa A, Okamura T, Kadowaki S, Kadowaki T, Hayakawa T, Kita Y, Abbott RD, Okayama A. Alcohol intake and 19-year mortality in diabetic men: NIPPON DATA80. Alcohol. 2009. 43(8):635-41. doi:10.1016/j.alcohol.2009.06.005. | Publication Date
165 | Nakaya N, Kurashima K, Yamaguchi J, Ohkubo T, Nishino Y, Tsubono Y, Shibuya D, Fukudo S, Fukao A, Tsuji I, Hisamichi S. Alcohol consumption and mortality in Japan: the Miyagi Cohort Study. J Epidemiol. 2004. 14 Suppl 1:S18-25. doi:10.2188/jea.14.s18. | Publication Date
166 | Nandi A, Glymour MM, Subramanian SV. Association among socioeconomic status, health behaviors, and all-cause mortality in the United States. Epidemiology. 2014. 25(2):170-7. doi:10.1097/ede.0000000000000038. | Comparator
167 | Nelson MR, Alkhateeb AN, Ryan P, Willson K, Gartlan JG, Reid CM. Physical activity, alcohol and tobacco use and associated cardiovascular morbidity and mortality in the Second Australian National Blood Pressure study cohort. Age Ageing. 2010. 39(1):112-6. doi:10.1093/ageing/afp186. | Outcome
168 | Nicholson A, Bobak M, Murphy M, Rose R, Marmot M. Alcohol consumption and increased mortality in Russian men and women: a cohort study based on the mortality of relatives. Bull World Health Organ. 2005. 83(11):812-9. doi:/s0042-96862005001100010. | Publication Date
169 | Nielsen NR, Schnohr P, Jensen G, Gronbaek M. Is the relationship between type of alcohol and mortality influenced by socio-economic status?. J Intern Med. 2004. 255(2):280-8. doi:10.1046/j.1365-2796.2003.01268.x. | Publication Date
170 | Nielsen NR, Thygesen LC, Johansen D, Jensen G, Gronbaek M. The influence of duration of follow-up on the association between alcohol and cause-specific mortality in a prospective cohort study. Ann Epidemiol. 2005. 15(1):44-55. doi:10.1016/j.annepidem.2004.04.002. | Publication Date
171 | Nordahl H, Lange T, Osler M, Diderichsen F, Andersen I, Prescott E, Tjonneland A, Frederiksen BL, Rod NH. Education and cause-specific mortality: the mediating role of differential exposure and vulnerability to behavioral risk factors. Epidemiology. 2014. 25(3):389-96. doi:10.1097/ede.0000000000000080. | Intervention/Exposure; Other (e.g., duplicative data, not primary research)
172 | Norstrom T, Razvodovsky Y. Per capita alcohol consumption and alcohol-related harm in Belarus, 1970-2005. Eur J Public Health. 2010. 20(5):564-8. doi:10.1093/eurpub/ckq011. | Intervention/Exposure; Comparator
173 | Nybo H, Petersen HC, Gaist D, Jeune B, Andersen K, McGue M, Vaupel JW, Christensen K. Predictors of mortality in 2,249 nonagenarians--the Danish 1905-Cohort Survey. J Am Geriatr Soc. 2003. 51(10):1365-73. doi:10.1046/j.1532-5415.2003.51453.x. | Publication Date
174 | Odegaard AO, Koh WP, Gross MD, Yuan JM, Pereira MA. Combined lifestyle factors and cardiovascular disease mortality in Chinese men and women: the Singapore Chinese health study. Circulation. 2011. 124(25):2847-54. doi:10.1161/circulationaha.111.048843. | Intervention/Exposure; Outcome
175 | Odegaard AO, Koh WP, Yuan JM, Pereira MA. Beverage habits and mortality in Chinese adults. J Nutr. 2015. 145(3):595-604. doi:10.3945/jn.114.200253. | Intervention/Exposure; Comparator
176 | Onat A, Hergenc G, Kucukdurmaz Z, Ugur M, Kaya Z, Can G, Yuksel H. Moderate and heavy alcohol consumption among Turks: long-term impact on mortality and cardiometabolic risk. Turk Kardiyol Dern Ars. 2009. 37(2):83-90. | Country
177 | Ostergren O, Martikainen P, Tarkiainen L, Elstad JI, Bronnum-Hansen H. Contribution of smoking and alcohol consumption to income differences in life expectancy: evidence using Danish, Finnish, Norwegian and Swedish register data. J Epidemiol Community Health. 2019. 73(4):334-339. doi:10.1136/jech-2018-211640. | Study Design; Intervention/Exposure; Outcome
178 | Ozasa K. Alcohol use and mortality in the Japan Collaborative Cohort Study for Evaluation of Cancer (JACC). i. 2007. 8 Suppl:81-8. | Publication Date
179 | Paganini-Hill A, Kawas CH, Corrada MM. Type of alcohol consumed, changes in intake over time and mortality: the Leisure World Cohort Study. Age Ageing. 2007. 36(2):203-9. doi:10.1093/ageing/afl184. | Publication Date
180 | Paganini-Hill A. Lifestyle practices and cardiovascular disease mortality in the elderly: the leisure world cohort study. i. 2011. 2011:983764. doi:10.4061/2011/983764. | Outcome
181 | Park S, Hong JP, Choi SH, Ahn MH. Clinical and laboratory predictors of all causes deaths and alcohol-attributable deaths among discharged alcohol-dependent patients. Alcohol Clin Exp Res. 2013. 37(2):270-5. doi:10.1111/j.1530-0277.2012.01943.x. | Intervention/Exposure; Health Status
182 | Paschall M, Lipton, RI. Wine preference and related health determinants in a U.S. national sample of young adults. Drug Alcohol Depend. 2005. 78(3):339-44. doi:10.1016/j.drugalcdep.2004.12.004. | Outcome
183 | Pedersen JO, Heitmann BL, Schnohr P, Gronbaek M. The combined influence of leisure-time physical activity and weekly alcohol intake on fatal ischaemic heart disease and all-cause mortality. Eur Heart J. 2008. 29(2):204-12. doi:10.1093/eurheartj/ehm574. | Publication Date
184 | Perez-Perez E, Cruz-Lopez L, Hernandez-Llanes NF, Gallegos-Cari A, Camacho-Solis RE, Mendoza-Melendez MA. Years of life lost (Yll) attributable to alcohol consumption in Mexico City. Cien Saude Colet. 2016. 21(1):37-44. doi:10.1590/141381232015211.09472015. | Intervention/Exposure
185 | Perlman F, Bobak M. Socioeconomic and behavioral determinants of mortality in posttransition Russia: a prospective population study. Ann Epidemiol. 2008. 18(2):92-100. doi:10.1016/j.annepidem.2007.07.093. | Publication Date
186 | Perreira KM, Sloan FA. Excess alcohol consumption and health outcomes: a 6-year follow-up of men over age 50 from the health and retirement study. Addiction. 2002. 97(3):301-10. doi:10.1046/j.1360-0443.2002.00067.x. | Publication Date
187 | Petersen KE, Johnsen NF, Olsen A, Albieri V, Olsen LK, Dragsted LO, Overvad K, Tjonneland A, Egeberg R. The combined impact of adherence to five lifestyle factors on all-cause, cancer and cardiovascular mortality: a prospective cohort study among Danish men and women. Br J Nutr. 2015. 113(5):849-58. doi:10.1017/s0007114515000070. | Intervention/Exposure
188 | Plavinski SL, Plavinskaya SI, Klimov AN. Social factors and increase in mortality in Russia in the 1990s: prospective cohort study. Bmj. 2003. 326(7401):1240-2. doi:10.1136/bmj.326.7401.1240. | Intervention/Exposure; Other (e.g., duplicative data, not primary research)
189 | Prinelli F, Yannakoulia M, Anastasiou CA, Adorni F, Di Santo SG, Musicco M, Scarmeas N, Correa Leite ML. Mediterranean diet and other lifestyle factors in relation to 20-year all-cause mortality: A cohort study in an Italian population. British Journal of Nutrition. 2015. 113(6):1003-1011. doi:10.1017/S0007114515000318. | Comparator
190 | Probst C, Rehm J. Alcohol use, opioid overdose and socioeconomic status in Canada: A threat to life expectancy?. Cmaj. 2018. 190(44):E1294-e1295. doi:10.1503/cmaj.180806. | Study Design; Other (e.g., duplicative data, not primary research)
191 | Rao TS, Andrade C. Alcohol intake, morbidity, and mortality. Indian J Psychiatry. 2016. 58(1):1-3. doi:10.4103/0019-5545.174352. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
192 | Razvodovsky YE. Alcohol attributable mortality in Belarus. Alcoholism. 2012. 48(1):13-22. | Intervention/Exposure
193 | Razvodovsky YE. Estimation of alcohol attributable fraction of mortality in Russia. Adicciones. 2012. 24(3):247-52. | Study Design; Intervention/Exposure
194 | Rehm J, Greenfield TK, Rogers JD. Average volume of alcohol consumption, patterns of drinking, and all-cause mortality: results from the US National Alcohol Survey. Am J Epidemiol. 2001. 153(1):64-71. doi:10.1093/aje/153.1.64. | Publication Date
195 | Rehm J, Mathers C, Popova S, Thavorncharoensap M, Teerawattananon Y, Patra J. Global burden of disease and injury and economic cost attributable to alcohol use and alcohol-use disorders. Lancet. 2009. 373(9682):2223-33. doi:10.1016/s0140-6736(09)60746-7. | Study Design; Intervention/Exposure
196 | Rehm J, Monteiro M. Alcohol consumption and burden of disease in the Americas: implications for alcohol policy. Rev Panam Salud Publica. 2005. 18(4-5):241-8. doi:10.1590/s1020-49892005000900003. | Intervention/Exposure; Outcome
197 | Rehm J, Patra J, Taylor, B. Harm, Benefits, and Net Effects on Mortality of Moderate Drinking of Alcohol Among Adults in Canada in 2002. Annals of Epidemiology. 2007. 17(5 SUPPL.):S81-S86. doi:10.1016/j.annepidem.2007.01.018. | Intervention/Exposure; Outcome
198 | Rehm J, Room R, Monteiro M, Gmel G, Graham K, Rehn N, Sempos, CT, Jernigan, D. Alcohol as a risk factor for global burden of disease. Eur Addict Res. 2003. 9(4):157-64. doi:10.1159/000072222. | Intervention/Exposure; Outcome
199 | Rehm J, Scafato, E. Indicators of alcohol consumption and attributable harm for monitoring and surveillance in European Union countries. Addiction. 2011. 106 Suppl 1:4-10. doi:10.1111/j.1360-0443.2010.03323.x. | Outcome
200 | Rehm J, Sulkowska U, Manczuk M, Boffetta P, Powles J, Popova S, Zatonski, W. Alcohol accounts for a high proportion of premature mortality in central and eastern Europe. Int J Epidemiol. 2007. 36(2):458-67. doi:10.1093/ije/dyl294. | Intervention/Exposure; Outcome
201 | Reile R, Stickley A, Leinsalu, M. Large variation in predictors of mortality by levels of self-rated health: Results from an 18-year follow-up study. Public Health. 2017. 145:59-66. doi:10.1016/j.puhe.2016.12.034. | Intervention/Exposure; Comparator
202 | Renaud S, Lanzmann-Petithory D, Gueguen R, Conard, P. Alcohol and mortality from all causes. Biol Res. 2004. 37(2):183-7. doi:10.4067/s0716-97602004000200002. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
203 | Renaud SC, Gueguen R, Conard P, Lanzmann-Petithory D, Orgogozo JM, Henry O. Moderate wine drinkers have lower hypertension-related mortality: a prospective cohort study in French men. Am J Clin Nutr. 2004. 80(3):621-5. doi:10.1093/ajcn/80.3.621. | Comparator
204 | Rey G, Boniol M, Jougla E. Estimating the number of alcohol-attributable deaths: methodological issues and illustration with French data for 2006. Addiction. 2010. 105(6):1018-29. doi:10.1111/j.1360-0443.2010.02910.x. | Outcome
205 | Ricci C, Wood A, Muller D, Gunter MJ, Agudo A, Boeing H, van der Schouw YT, Warnakula S, Saieva C, Spijkerman A, Sluijs I, Tjonneland A, Kyro C, Weiderpass E, Kuhn T, Kaaks R, Sanchez MJ, Panico S, Agnoli C, Palli D, Tumino R, Engstrom G, Melander O, Bonnet F, Boer JMA, Key TJ, Travis RC, Overvad K, Verschuren WMM, Quiros JR, Trichopoulou A, Papatesta, EM, Peppa E, Iribas CM, Gavrila D, Forslund AS, Jansson JH, Matullo G, Arriola L, Freisling H, Lassale C, Tzoulaki I, Sharp SJ, Forouhi, NG, Langenberg C, Saracci R, Sweeting M, Brennan P, Butterworth AS, Riboli E, Wareham NJ, Danesh J, Ferrari P. Alcohol intake in relation to non-fatal and fatal coronary heart disease and stroke: EPIC-CVD case-cohort study. Bmj. 2018. 361:k934. doi:10.1136/bmj.k934. | Outcome
206 | Ringmets I, Tuusov J, Lang K, Vali M, Parna K, Tonisson M, Helander A, McKee M, Leon DA. Alcohol and premature death in Estonian men: a study of forensic autopsies using novel biomarkers and proxy informants. BMC Public Health. 2012. 12:146. doi:10.1186/1471-2458-12-146. | Intervention/Exposure; Outcome
207 | Rizzuto D, Orsini N, Qiu C, Wang HX, Fratiglioni L. Lifestyle, social factors, and survival after age 75: population based study. Bmj. 2012. 345:e5568. doi:10.1136/bmj.e5568. | Comparator
208 | Robinson M, Shipton D, Walsh D, Whyte B, McCartney G. Regional alcohol consumption and alcohol-related mortality in Great Britain: novel insights using retail sales data. BMC Public Health. 2015. 15:1. doi:10.1186/1471-2458-15-1. | Intervention/Exposure
209 | Rogers RG, Boardman JD, Pendergast PM, Lawrence EM. Drinking problems and mortality risk in the United States. Drug Alcohol Depend. 2015. 151:38-46. doi:10.1016/j.drugalcdep.2015.02.039. | Intervention/Exposure
210 | Romelsjo A, Allebeck P, Andreasson S, Leifman A. Alcohol, mortality and cardiovascular events in a 35 year follow-up of a nationwide representative cohort of 50,000 Swedish conscripts up to age 55. Alcohol Alcohol. 2012. 47(3):322-7. doi:10.1093/alcalc/ags021. | Comparator
211 | Rosen M, Haglund B. Follow-up of an age-period-cohort analysis on alcohol-related mortality trends in Sweden 1970-2015 with predictions to 2025. Scand J Public Health. 2019. 47(4):446-451. doi:10.1177/1403494817752521. | Intervention/Exposure
212 | Ruf E, Baumert J, Meisinger C, Doring A, Ladwig KH. Are psychosocial stressors associated with the relationship of alcohol consumption and all-cause mortality?. BMC Public Health. 2014. 14:312. doi:10.1186/1471-2458-14-312. | Comparator
213 | Ryu M, Gombojav B, Nam CM, Lee Y, Han K. Modifying effects of resting heart rate on the association of binge drinking with all-cause and cardiovascular mortality in older Korean men: the Kangwha Cohort Study. J Epidemiol. 2014. 24(4):274-80. doi:10.2188/jea.je20130101. | Comparator
214 | Sadakane A, Gotoh T, Ishikawa S, Nakamura Y, Kayaba K. Amount and frequency of alcohol consumption and all-cause mortality in a Japanese population: the JMS Cohort Study. J Epidemiol. 2009. 19(3):107-15. doi:10.2188/jea.je20081003. | Publication Date
215 | Saito E, Inoue M, Sawada N, Charvat H, Shimazu T, Yamaji T, Iwasaki M, Sasazuki S, Mizoue T, Iso H, Tsugane S. Impact of Alcohol Intake and Drinking Patterns on Mortality From All Causes and Major Causes of Death in a Japanese Population. J Epidemiol. 2018. 28(3):140-148. doi:10.2188/jea.JE20160200. | Intervention/Exposure
216 | Sakaue S, Akiyama M, Hirata M, Matsuda K, Murakami Y, Kubo M, Kamatani Y, Okada Y. Functional variants in ADH1B and ALDH2 are non-additively associated with all-cause mortality in Japanese population. Eur J Hum Genet. 2019. doi:10.1038/s41431-019-0518-y. | Intervention/Exposure
217 | Schnohr C, Hojbjerre L, Riegels M, Ledet L, Larsen T, Schultz-Larsen K, Petersen L, Prescott E, Gronbaek M. Does educational level influence the effects of smoking, alcohol, physical activity, and obesity on mortality? A prospective population study. Scand J Public Health. 2004. 32(4):250-6. doi:10.1080/14034940310019489. | Publication Date
218 | Schooling CM, Sun W, Ho SY, Chan WM, Tham MK, Ho KS, Leung GM, Lam TH. Moderate alcohol use and mortality from ischaemic heart disease: a prospective study in older Chinese people. PLoS One. 2008. 3(6):e2370. doi:10.1371/journal.pone.0002370. | Outcome
219 | Sempos CT, Rehm J, Wu T, Crespo CJ, Trevisan M. Average volume of alcohol consumption and all-cause mortality in African Americans: the NHEFS cohort. Alcohol Clin Exp Res. 2003. 27(1):88-92. doi:10.1097/01.Alc.0000046597.92232.73. | Publication Date
220 | Sethi M, Heyer JH, Wall S, DiMaggio C, Shinseki M, Slaughter D, Frangos SG. Alcohol use by urban bicyclists is associated with more severe injury, greater hospital resource use, and higher mortality. Alcohol. 2016. 53:1-7. doi:10.1016/j.alcohol.2016.03.005. | Intervention/Exposure; Outcome
221 | Shaw BA, Agahi N. A prospective cohort study of health behavior profiles after age 50 and mortality risk. BMC public health. 2012. 12:803. | Intervention/Exposure; Comparator
222 | Shield KD, Gmel G, Gmel G, Makela P, Probst C, Room R, Rehm J. Life-time risk of mortality due to different levels of alcohol consumption in seven European countries: implications for low-risk drinking guidelines. Addiction. 2017. 112(9):1535-1544. doi:10.1111/add.13827. | Intervention/Exposure
223 | Shield KD, Gmel G, Kehoe-Chan T, Dawson DA, Grant BF, Rehm J. Mortality and potential years of life lost attributable to alcohol consumption by race and sex in the United States in 2005. PLoS One. 2013. 8(1):e51923. doi:10.1371/journal.pone.0051923. | Study Design; Intervention/Exposure; Outcome
224 | Shield KD, Kehoe T, Taylor B, Patra J, Rehm J. Alcohol-attributable burden of disease and injury in Canada, 2004. Int J Public Health. 2012. 57(2):391-401. doi:10.1007/s00038-011-0247-7. | Intervention/Exposure; Outcome
225 | Shield KD, Rehm J, Gmel G, Rehm MX, Allamani A. Alcohol consumption, alcohol dependence, and related mortality in Italy in 2004: effects of treatment-based interventions on alcohol dependence. Subst Abuse Treat Prev Policy. 2013. 8:21. doi:10.1186/1747-597x-8-21. | Intervention/Exposure; Comparator
226 | Shield KD, Rehm J. Russia-specific relative risks and their effects on the estimated alcohol-attributable burden of disease. BMC Public Health. 2015. 15:482. doi:10.1186/s12889-015-1818-y. | Intervention/Exposure; Outcome
227 | Shield KD, Taylor B, Kehoe T, Patra J, Rehm J. Mortality and potential years of life lost attributable to alcohol consumption in Canada in 2005. BMC Public Health. 2012. 12:91. doi:10.1186/1471-2458-12-91. | Intervention/Exposure; Comparator
228 | Sidorenkov O, Nilssen O, Grjibovski AM. Determinants of cardiovascular and all-cause mortality in northwest Russia: a 10-year follow-up study. Ann Epidemiol. 2012. 22(1):57-65. doi:10.1016/j.annepidem.2011.08.008. | Comparator
229 | Sidorenkov O, Nilssen O, Grjibovski AM. Metabolic syndrome in Russian adults: associated factors and mortality from cardiovascular diseases and all causes. BMC Public Health. 2010. 10:582. doi:10.1186/1471-2458-10-582. | Intervention/Exposure; Outcome
230 | Simons LA, McCallum J, Friedlander Y, Ortiz M, Simons J. Moderate alcohol intake is associated with survival in the elderly: the Dubbo Study. Med J Aust. 2000. 173(3):121-4. | Publication Date
231 | Simons LA, Simons J, Friedlander Y, McCallum J. Predictors of long-term mortality in the elderly: the Dubbo Study. Intern Med J. 2011. 41(7):555-60. doi:10.1111/j.1445-5994.2009.02106.x. | Intervention/Exposure; Comparator
232 | Sipetic S, Bjegovic-Mikanovic V, Vlajinac H, Marinkovic J, Jankovic S, Terzic Z, Atanackovic-Markovic Z, Saulic A, Laaser U. The burden of disease preventable by risk factor reduction in Serbia. Vojnosanit Pregl. 2013. 70(5):445-51. doi:10.2298/vsp111024049s. | Outcome
233 | Sipila P, Rose RJ, Kaprio J. Drinking and mortality: long-term follow-up of drinking-discordant twin pairs. Addiction. 2016. 111(2):245-54. doi:10.1111/add.13152. | Comparator
234 | Smigielski J, Bielecki W, Drygas W. Health and life style-related determinants of survival rate in the male residents of the city of Lodz. Int J Occup Med Environ Health. 2013. 26(3):337-48. doi:10.2478/s13382-013-0104-4. | Comparator
235 | Smigielski J, Jegier A, Hanke W, Bielecki W, Drygas W. The effect of selected lifestyle factors and diet on mortality of men with documented physical fitness in the city of Lodz. Int J Occup Med Environ Health. 2013. 26(4):535-44. doi:10.2478/s13382-013-0112-4. | Sample size
236 | Sofi F, Abbate R, Gensini GF, Casini A, Trichopoulou A, Bamia C. Identification of change-points in the relationship between food groups in the Mediterranean diet and overall mortality: an ‘a posteriori’ approach. Eur J Nutr. 2012. 51(2):167-72. doi:10.1007/s00394-011-0202-7. | Intervention/Exposure; Outcome
237 | Sotos-Prieto M, Mattei J, Cook NR, Hu FB, Willett WC, Chiuve SE, Rimm EB, Sesso HD. Association Between a 20-Year Cardiovascular Disease Risk Score Based on Modifiable Lifestyles and Total and Cause-Specific Mortality Among US Men and Women. J Am Heart Assoc. 2018. 7(21):e010052. doi:10.1161/jaha.118.010052. | Intervention/Exposure; Comparator
238 | Sovic S, Vitale K, Brborovic O, Dzakula A, Tiljak H. Association of behavioral cardiovascular risk factors with mortality in Croatian adult population: the CroHort study. Coll Antropol. 2012. 36 Suppl 1:177-82. doi:10.5671/ca.2012361s.177. | Intervention/Exposure; Comparator
239 | Stahre M, Roeber J, Kanny D, Brewer RD, Zhang X. Contribution of excessive alcohol consumption to deaths and years of potential life lost in the United States. Prev Chronic Dis. 2014. 11:E109. doi:10.5888/pcd11.130293. | Intervention/Exposure; Outcome
240 | StatBite: Alcohol-related deaths from chronic causes among American Indians and Alaska Natives. J Natl Cancer Inst. 2008. 100(19):1349. doi:10.1093/jnci/djn350. | Study Design; Publication Status
241 | Strandberg AY, Strandberg TE, Salomaa VV, Pitkala K, Miettinen TA. Alcohol consumption, 29-y total mortality, and quality of life in men in old age. Am J Clin Nutr. 2004. 80(5):1366-71. doi:10.1093/ajcn/80.5.1366. | Publication Date
242 | Streppel MT, Ocke MC, Boshuizen HC, Kok FJ, Kromhout D. Long-term wine consumption is related to cardiovascular mortality and life expectancy independently of moderate alcohol intake: the Zutphen Study. J Epidemiol Community Health. 2009. 63(7):534-40. doi:10.1136/jech.2008.082198. | Publication Date
243 | Stringhini S, Carmeli C, Jokela M, Avendaño M, Muennig P, Guida F, Ricceri F, d’Errico A, Barros H, Bochud M, Chadeau-Hyam M, Clavel-Chapelon F, Costa G, Delpierre C, Fraga S, Goldberg M, Giles GG, Krogh V, Kelly-Irving M, Layte R, Lasserre AM, Marmot MG, Preisig M, Shipley MJ, Vollenweider P, Zins M, Kawachi I, Steptoe A, Mackenbach JP, Vineis P, Kivimäki M, Alenius H, Avendano M, Carra L, Castagné R, Courtin E, Dugué PA, Elliott P, Gares V, Giles G, Greco D, Hodge A, Irving MK, Karisola P, Lang T, Lepage B, Mackenbach J, McCrory C, Milne R, Nusselder W, Panico S, Petrovic D, Polidoro S, Raitakari O, Ribeiro AI, Robinson O, Valverde JR, Sacerdote C, Satolli R, Severi G, Tumino R. Socioeconomic status and the 25 × 25 risk factors as determinants of premature mortality: a multicohort study and meta-analysis of 1·7 million men and women. The Lancet. 2017. 389(10075):1229-1237. doi:10.1016/S0140-6736(16)32380-7. | Comparator; Outcome
244 | Stringhini S, Sabia S, Shipley M, Brunner E, Nabi H, Kivimaki M, Singh-Manoux A. Association of socioeconomic position with health behaviors and mortality. Jama. 2010. 303(12):1159-66. doi:10.1001/jama.2010.297. | Study design
245 | Stringhini S, Zaninotto P, Kumari M, Kivimaki M, Lassale C, Batty GD. Socio-economic trajectories and cardiovascular disease mortality in older people: the English Longitudinal Study of Ageing. Int J Epidemiol. 2018. 47(1):36-46. doi:10.1093/ije/dyx106. | Comparator
246 | Suadicani P, Hein HO, Gyntelberg F. Wine intake, ABO phenotype, and risk of ischemic heart disease and all-cause mortality: the Copenhagen Male Study--a 16-year follow-up. Alcohol. 2008. 42(7):575-82. doi:10.1016/j.alcohol.2008.05.007. | Publication Date
247 | Suadicani P, Hein HO, von Eyben FE, Gyntelberg F. Metabolic and lifestyle predictors of ischemic heart disease and all-cause mortality among normal weight, overweight, and obese men: a 16-year follow-up in the Copenhagen Male Study. Metab Syndr Relat Disord. 2009. 7(2):97-104. doi:10.1089/met.2008.0041. | Intervention/Exposure
248 | Sull JW, Yi SW, Nam CM, Ohrr H. Binge drinking and mortality from all causes and cerebrovascular diseases in korean men and women: a Kangwha cohort study. Stroke. 2009. 40(9):2953-8. doi:10.1161/strokeaha.109.556027. | Publication Date
249 | Sun W, Schooling CM, Chan WM, Ho KS, Lam TH, Leung GM. Moderate alcohol use, health status, and mortality in a prospective Chinese elderly cohort. Ann Epidemiol. 2009. 19(6):396-403. doi:10.1016/j.annepidem.2009.01.011. | Publication Date
250 | Tae HK, Shin J, Noh S, Kyo JS, Park JK, Ahn JS, Min S. Alcohol-related mortality in a rural community in Korea over an eight-year period. Psychiatry Investigation. 2007. 4(2):96-103. | Publication Date
251 | Taylor B, Rehm J, Room R, Patra J, Bondy S. Determination of lifetime injury mortality risk in Canada in 2002 by drinking amount per occasion and number of occasions. Am J Epidemiol. 2008. 168(10):1119-25; discussion 1126-31. doi:10.1093/aje/kwn215. | Intervention/Exposure; Outcome
252 | Taylor BJ, Shield KD, Rehm JT. Combining best evidence: a novel method to calculate the alcohol-attributable fraction and its variance for injury mortality. BMC Public Health. 2011. 11:265. doi:10.1186/1471-2458-11-265. | Outcome
253 | Taylor J. Effects of alcohol on cardiovascular disease: originally thought to be cardioprotective, the pendulum is now swinging against alcohol, with more deaths due to drinking than lives saved. Eur Heart J. 2013. 34(9):627-9. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
254 | Theobald H, Bygren, LO, Carstensen J, Engfeldt P. A moderate intake of wine is associated with reduced total mortality and reduced mortality from cardiovascular disease. J Stud Alcohol. 2000. 61(5):652-6. doi:10.15288/jsa.2000.61.652. | Publication Date
255 | Theobald H, Johansson SE, Bygren LO, Engfeldt P. The effects of alcohol consumption on mortality and morbidity: a 26-year follow-up study. J Stud Alcohol. 2001. 62(6):783-9. doi:10.15288/jsa.2001.62.783. | Publication Date
256 | Thomson CA, McCullough ML, Wertheim BC, Chlebowski RT, Martinez ME, Stefanick ML, Rohan TE, Manson JE, Tindle HA, Ockene J, Vitolins MZ, Wactawski-Wende J, Sarto GE, Lane DS, Neuhouser ML. Nutrition and physical activity cancer prevention guidelines, cancer risk, and mortality in the women’s health initiative. Cancer Prev Res (Phila). 2014. 7(1):42-53. doi:10.1158/1940-6207.Capr-13-0258. | Intervention/Exposure
257 | Thorpe RJ, Jr, Wilson-Frederick SM, Bowie JV, Coa K, Clay OJ, LaVeist TA, Whitfield KE. Health behaviors and all-cause mortality in African American men. Am J Mens Health. 2013. 7(4 Suppl):8s-18s. doi:10.1177/1557988313487552. | Comparator
258 | Thygesen LC, Johansen C, Keiding N, Giovannucci E, Gronbaek M. Effects of sample attrition in a longitudinal study of the association between alcohol intake and all-cause mortality. Addiction. 2008. 103(7):1149-59. doi:10.1111/j.13600443.2008.02241.x. | Publication Date
259 | Tognon G, Lissner L, Saebye D, Walker KZ, Heitmann BL. The Mediterranean diet in relation to mortality and CVD: a Danish cohort study. Br J Nutr. 2014. 111(1):151-9. doi:10.1017/s0007114513001931. | Comparator
260 | Tolstrup JS, Jensen MK, Tjonneland A, Overvad K, Gronbaek M. Drinking pattern and mortality in middle-aged men and women. Addiction. 2004. 99(3):323-30. doi:10.1111/j.1360-0443.2003.00667.x. | Publication Date
261 | Tolvanen E, Seppa K, Lintonen T, Paavilainen P, Jylha M. Old people, alcohol use and mortality. A ten-year prospective study. Aging Clin Exp Res. 2005. 17(5):426-33. doi:10.1007/bf03324633. | Publication Date
262 | Tomkins S, Collier T, Oralov A, Saburova L, McKee M, Shkolnikov V, Kiryanov N, Leon DA. Hazardous alcohol consumption is a major factor in male premature mortality in a typical Russian city: prospective cohort study 2003-2009. PLoS One. 2012. 7(2):e30274. doi:10.1371/journal.pone.0030274. | Intervention/Exposure
263 | Trevisan M, Schisterman E, Mennotti A, Farchi G, Conti S. Drinking pattern and mortality: the Italian Risk Factor and Life Expectancy pooling project. Ann Epidemiol. 2001. 11(5):312-9. doi:10.1016/s1047-2797(00)00183-6. | Intervention/Exposure; Comparator
264 | Trias-Llimos S, Janssen F. Alcohol and gender gaps in life expectancy in eight Central and Eastern European countries. Eur J Public Health. 2018. 28(4):687-692. doi:10.1093/eurpub/cky057. | Intervention/Exposure
265 | Trias-Llimos S, Martikainen P, Makela P, Janssen F. Comparison of different approaches for estimating age-specific alcohol-attributable mortality: The cases of France and Finland. PLoS One. 2018. 13(3):e0194478. doi:10.1371/journal.pone.0194478. | Intervention/Exposure
266 | Trichopoulou A, Bamia C, Trichopoulos D. Anatomy of health effects of Mediterranean diet: Greek EPIC prospective cohort study. Bmj. 2009. 338:b2337. doi:10.1136/bmj.b2337. | Publication Date
267 | Tsubono Y, Koizumi Y, Nakaya N, Fujita K, Takahashi H, Hozawa A, Suzuki Y, Kuriyama S, Tsuji I, Fukao A, Hisamichi S. Health practices and mortality in Japan: combined effects of smoking, drinking, walking and body mass index in the Miyagi Cohort Study. J Epidemiol. 2004. 14 Suppl 1:S39-45. doi:10.2188/jea.14.s39. | Intervention/Exposure
268 | Turiano NA, Chapman BP, Gruenewald TL, Mroczek DK. Personality and the leading behavioral contributors of mortality. Health Psychol. 2015. 34(1):51-60. doi:10.1037/hea0000038. | Intervention/Exposure
269 | Tverdal A, Magnus P, Selmer R, Thelle D. Consumption of alcohol and cardiovascular disease mortality: a 16 year follow-up of 115,592 Norwegian men and women aged 40-44 years. Eur J Epidemiol. 2017. 32(9):775-783. doi:10.1007/s10654-017-0313-4. | Outcome
270 | Urtamo A, Jyväkorpi SK, Kautiainen H, Pitkälä KH, Strandberg TE. Major cardiovascular disease (CVD) risk factors in midlife and extreme longevity. Aging Clinical and Experimental Research. 2020. 32(2):299-304. doi:10.1007/s40520-019-01364-7. | Intervention/exposure; Sample size
271 | van Dam RM, Li T, Spiegelman D, Franco OH, Hu FB. Combined impact of lifestyle factors on mortality: prospective cohort study in US women. Bmj. 2008. 337:a1440. doi:10.1136/bmj.a1440. | Publication Date
272 | Veronese N, Li Y, Manson JE, Willett WC, Fontana L, Hu FB. Combined associations of body weight and lifestyle factors with all cause and cause specific mortality in men and women: prospective cohort study. Bmj. 2016. 355:i5855. doi:10.1136/bmj.i5855. | Intervention/Exposure
273 | Vetrano DL, Collamati A, Magnavita N, Sowa A, Topinkova E, Finne-Soveri H, van der Roest HG, Tobiasz-Adamczyk B, Giovannini S, Ricciardi W, Bernabei R, Onder G, Poscia A. Health determinants and survival in nursing home residents in Europe: Results from the SHELTER study. Maturitas. 2018. 107:19-25. doi:10.1016/j.maturitas.2017.09.014. | Intervention/Exposure; Health Status
274 | Walker S. Russia’s alcohol problem. Bmj. 2011. 343:d5240. doi:10.1136/bmj.d5240. | Study Design
275 | Wannamethee SG, Shaper AG. Taking up regular drinking in middle age: effect on major coronary heart disease events and mortality. Heart. 2002. 87(1):32-6. doi:10.1136/heart.87.1.32. | Publication Date
276 | Waskiewicz A, Sygnowska E, Drygas W. Relationship between alcohol consumption and cardiovascular mortality--the Warsaw Pol-MONICA Project. Kardiol Pol. 2004. 60(6):552-62; discussion 563. | Publication Date
277 | Wellmann J, Heidrich J, Berger K, Doring A, Heuschmann PU, Keil U. Changes in alcohol intake and risk of coronary heart disease and all-cause mortality in the MONICA/KORA-Augsburg cohort 1987-97. Eur J Cardiovasc Prev Rehabil. 2004. 11(1):48-55. doi:10.1097/01.hjr.0000118174.70522.20. | Publication Date
278 | White J, Greene G, Kivimaki M, Batty GD. Association between changes in lifestyle and all-cause mortality: the Health and Lifestyle Survey. J Epidemiol Community Health. 2018. 72(8):711-714. doi:10.1136/jech-2017-210363. | Intervention/Exposure
279 | Whitfield JB, Heath AC, Madden PAF, Landers JG, Martin NG. Effects of high alcohol intake, alcohol-related symptoms and smoking on mortality. Addiction. 2018. 113(1):158-166. doi:10.1111/add.14008. | Comparator
280 | Whitley E, Batty GD, Hunt K, Popham F, Benzeval M. The role of health behaviours across the life course in the socioeconomic patterning of all-cause mortality: the west of Scotland twenty-07 prospective cohort study. Ann Behav Med. 2014. 47(2):148-57. doi:10.1007/s12160-013-9539-x. | Intervention/Exposure
281 | Williams EC, Bradley KA, Gupta S, Harris AHS. Association between alcohol screening scores and mortality in Black, Hispanic, and White male veterans. Alcoholism: Clinical and Experimental Research. 2012. 36(12):2132-2140. doi:10.1111/j.1530-0277.2012.01842.x. | Intervention/Exposure
282 | Wojtyniak B, Moskalewicz J, Stokwiszewski J, Rabczenko D. Gender-specific mortality associated with alcohol consumption in Poland in transition. Addiction. 2005. 100(12):1779-89. doi:10.1111/j.1360-0443.2005.01247.x. | Intervention/Exposure; Outcome
283 | Woo J, Ho SC, Yu AL. Lifestyle factors and health outcomes in elderly Hong Kong Chinese aged 70 years and over. Gerontology. 2002. 48(4):234-40. doi:10.1159/000058356. | Publication Date
284 | Wood AM, Kaptoge S, Butterworth AS, Willeit P, Warnakula S, Bolton T, Paige E, Paul DS, Sweeting M, Burgess S, Bell S, Astle W, Stevens D, Koulman A, Selmer RM, Verschuren WMM, Sato S, Njølstad I, Woodward M, Salomaa V, Nordestgaard BG, Yeap BB, Fletcher A, Melander O, Kuller LH, Balkau B, Marmot M, Koenig W, Casiglia E, Cooper C, Arndt V, Franco OH, Wennberg P, Gallacher J, de la Cámara AG, Völzke H, Dahm CC, Dale CE, Bergmann MM, Crespo CJ, van der Schouw YT, Kaaks R, Simons LA, Lagiou P, Schoufour JD, Boer JMA, Key TJ, Rodriguez B, Moreno-Iribas C, Davidson KW, Taylor JO, Sacerdote C, Wallace RB, Quiros JR, Tumino R, Blazer DG, Linneberg A, Daimon M, Panico S, Howard B, Skeie G, Strandberg T, Weiderpass E, Psaty BM, Kromhout D, Salamanca-Fernandez E, Kiechl S, Krumholz HM, Grioni S, Palli D, Huerta JM, Price J, Sundström J, Arriola L, Arima H, Travis RC, Panagiotakos DB, Karakatsani A, Trichopoulou A, Kühn T, Grobbee DE, Barrett-Connor E, van Schoor N, Boeing H, Overvad K, Kauhanen J, Wareham N, Langenberg C, Forouhi N, Wennberg M, Després, JP, Cushman M, Cooper JA, Rodriguez CJ, Sakurai M, Shaw JE, Knuiman M, Voortman T, Meisinger C, Tjønneland A, Brenner H, Palmieri L, Dallongeville J, Brunner, EJ, Assmann G, Trevisan M, Gillum RF, Ford I, Sattar N, Lazo M, Thompson SG, Ferrari P, Leon, DA, Davey Smith G, Peto R, Jackson R, Banks E, Di Angelantonio E, Danesh J, Veikko S, Gómez de la Cámara A, Rimm EB, Dallongeville JP, Gillumn RF, Ford IF, Thompson S. Risk thresholds for alcohol consumption: combined analysis of individual-participant data for 599 912 current drinkers in 83 prospective studies. The Lancet. 2018. 391(10129):1513-1523. doi:10.1016/S0140-6736(18)30134-X. | Duplicate
285 | Woodside JV, Yarnell JW, Patterson CC, Arveiler D, Amouyel P, Ferrieres J, Kee F, Evans A, Bingham A, Ducimetiere P. Do lifestyle behaviours explain socioeconomic differences in all-cause mortality, and fatal and non-fatal cardiovascular events? Evidence from middle aged men in France and Northern Ireland in the PRIME Study. Prev Med. 2012. 54(3-4):247-53. doi:10.1016/j.ypmed.2012.01.017. | Intervention/Exposure
286 | Wu CY, Chou YC, Huang N, Chou YJ, Hu HY, Li CP. Association of body mass index with all-cause and cardiovascular disease mortality in the elderly. PLoS One. 2014. 9(7):e102589. doi:10.1371/journal.pone.0102589. | Intervention/Exposure; Comparator
287 | Wyshak G. Behavioral practices and mortality in women former college athletes and nonathletes. Health Care Women Int. 2003. 24(9):808-21. doi:10.1080/07399330390229920. | Intervention/Exposure
288 | Xu WH, Zhang XL, Gao YT, Xiang YB, Gao LF, Zheng W, Shu XO. Joint effect of cigarette smoking and alcohol consumption on mortality. Prev Med. 2007. 45(4):313-9. doi:10.1016/j.ypmed.2007.05.015. | Publication Date
289 | Yang L, Zhou M, Sherliker P, Cai Y, Peto R, Wang L, Millwood I, Smith M, Hu Y, Yang G, Chen, Z. Alcohol drinking and overall and cause-specific mortality in China: nationally representative prospective study of 220,000 men with 15 years of follow-up. Int J Epidemiol. 2012. 41(4):1101-13. doi:10.1093/ije/dys075. | Country
290 | Yayci N, Agritmis H, Turla A, Koc, S. Fatalities due to methyl alcohol intoxication in Turkey: an 8-year study. Forensic Sci Int. 2003. 131(1):36-41. doi:10.1016/s0379-0738(02)00376-6. | Intervention/Exposure; Outcome; Country
291 | Yi, SW, Yoo, SH, Sull, JW, Ohrr, H. Association between alcohol drinking and cardiovascular disease mortality and all-cause mortality: Kangwha Cohort Study. J Prev Med Public Health. 2004. 37(2):120-6. | Language
292 | Zaccardi F, Franks PW, Dudbridge F, Davies MJ, Khunti K, Yates T. Mortality risk comparing walking pace to handgrip strength and a healthy lifestyle: A UK Biobank study. Eur J Prev Cardiol. 2019:2047487319885041. doi:10.1177/2047487319885041. | Other (e.g., duplicative data, not primary research)
293 | Zaridze D, Lewington S, Boroda A, Scelo G, Karpov R, Lazarev A, Konobeevskaya I, Igitov V, Terechova T, Boffetta P, Sherliker P, Kong X, Whitlock G, Boreham J, Brennan P, Peto R. Alcohol and mortality in Russia: prospective observational study of 151,000 adults. Lancet. 2014. 383(9927):1465-1473. doi:10.1016/s0140-6736(13)62247-3. | Outcome
294 | Zaridze D. Alcohol and health in Russia: good news at last. Lancet. 2017. 390(10102):1616-1618. doi:10.1016/s01406736(17)32387-5. | Study Design; Publication Status; Other (e.g., duplicative data, not primary research)
295 | Zazpe I, Sanchez-Tainta A, Toledo E, Sanchez-Villegas A, Martinez-Gonzalez MA. Dietary patterns and total mortality in a Mediterranean cohort: the SUN project. J Acad Nutr Diet. 2014. 114(1):37-47. doi:10.1016/j.jand.2013.07.024. | Intervention/Exposure
296 | Zhang QL, Zhao LG, Zhang W, Li HL, Gao J, Han LH, Zheng W, Shu XO, Xiang YB. Combined impact of known lifestyle factors on total and cause-specific mortality among Chinese men: a prospective cohort study. Sci Rep. 2017. 7(1):5293. doi:10.1038/s41598-017-05079-5. | Country
297 | Zhao G, Ronda E, Cea L, Pulido J, Barrio G, Regidor E. Mortality by cause of death and risk behaviors in farmers versus non-farmers: the importance of avoiding the healthy worker effect. Int Arch Occup Environ Health. 2019. 92(4):599-608. doi:10.1007/s00420-018-1396-2. | Intervention/Exposure
298 | Zhao W, Ukawa S, Okada E, Wakai K, Kawamura T, Ando M, Tamakoshi A. The associations of dietary patterns with all-cause mortality and other lifestyle factors in the elderly: An age-specific prospective cohort study. Clin Nutr. 2019. 38(1):288-296. doi:10.1016/j.clnu.2018.01.018. | Intervention/Exposure
299 | Zhu N, Yu C, Guo Y, Bian Z, Han Y, Yang L, Chen Y, Du H, Li H, Liu F, Chen J, Chen Z, Lv J, Li L. Adherence to a healthy lifestyle and all-cause and cause-specific mortality in Chinese adults: a 10-year prospective study of 0.5 million people. Int J Behav Nutr Phys Act. 2019. 16(1):98. doi:10.1186/s12966-019-0860-z. | Country

ix Dietary Guidelines Advisory Committee. 2020. Scientific Report of the 2020 Dietary Guidelines Advisory Committee: Advisory Report to the Secretary of Agriculture and the Secretary of Health and Human Services. U.S. Department of Agriculture, Agricultural Research Service, Washington, DC.

x The Human Development classification was based on the Human Development Index (HDI) ranking from the year the study intervention occurred or data were collected (UN Development Program. HDI 1990-2017 HDRO calculations based on data from UNDESA (2017a), UNESCO Institute for Statistics (2018), United Nations Statistics Division (2018b), World Bank (2018b), Barro and Lee (2016) and IMF (2018). Available from: http://hdr.undp.org/en/data). If the study did not report the year in which the intervention occurred or data were collected, the HDI classification for the year of publication was applied. HDI values are available from 1980, and then from 1990 to present. If a study was conducted prior to 1990, the HDI classification from 1990 was applied. If a study was conducted in 2018 or 2019, the most current HDI classification was applied. When a country was not included in the HDI ranking, the current country classification from the World Bank was used instead (The World Bank. World Bank country and lending groups. Available from: https://datahelpdesk.worldbank.org/knowledgebase/articles/906519-world-country-and-lending-groups).