# ACKNOWLEDGEMENTS

Infant milk-feeding practices Technical Expert Collaborative (TEC):

- Steve A. Abrams, MD, Dell Medical School at the University of Texas at Austin
- Sue Anderson, PhD, US Food and Drug Administration (06/2015-12/2015)
- Leila Beker, PhD, RD, contractor for US Food and Drug Administration
- Kirsi M Järvinen, MD, PhD, University of Rochester Medical Center
- Laurie A. Nommsen-Rivers, PhD, RD, IBCLC, University of Cincinnati College of Allied Health Sciences (starting 09/2015)
- Kimberly O. O’Brien, PhD, Division of Nutritional Sciences, Cornell University
- Emily Oken, MD, MPH, Division of Chronic Disease Research Across the Lifecourse, Department of Population Medicine, Harvard Medical School and Harvard Pilgrim Health Care Institute, Department of Nutrition, Harvard School of Public Health
- Rafael Pérez-Escamilla, PhD, Department of Social and Behavioral Sciences, Yale School of Public Health
- Ekhard E. Ziegler, MD, Department of Pediatrics, The University of Iowa

Nutrition Evidence Systematic Review (NESR) team:

- Darcy Güngör^1^, MS, Panum Group, Lead analyst
- Perrine Nadaud^1^, PhD, Panum Group, Analyst
- Carol Dreibelbis^1^, MPH, Panum Group, Analyst (starting 01/2016)
- Concetta LaPergola^1^, MS, Panum Group, Analyst (starting 11/2016)
- Nancy Terry, MLS, NIH, Librarian
- Yat Ping Wong, MLS, MPH, USDA, Librarian

Project leads:

- Joanne Spahn, MS, USDA
- Kellie O. Casavale, PhD, RD, HHS
- Eve Essery Stoody, PhD, USDA

Federal Expert Group (FEG)-Technical Expert Collaborative (TEC) liaisons:

- Leila Beker, PhD, RD, US Food and Drug Administration (6/2015-4/2016)
- Tova Jacobovits, MS, RD, US Food and Drug Administration (starting 4/2016)

SAA, SA, LB, KMJ, LAN-R, KOO’B, EO, RP-E, EEZ, DG, PN, and JS participated in establishing the research questions, analytic framework, and study inclusion and exclusion criteria. YPW and NT developed the literature search strategy and conducted the literature search. PN, CD, and DG screened search results and identified studies for inclusion. DG and PN extracted data and assessed risk of bias for included studies. SAA, LB, TJ, KMJ, LAN-R, KOO’B, EO, RP-E, and EEZ reviewed and provided substantive feedback on all systematic review materials, including the synthesis of the body of evidence, conclusion statement, and grade of the strength of the evidence. DG and PN prepared this report and JMS provided oversight. All authors critically reviewed and approved the final report. The authors declare no conflicts of interest.

We thank Katherine Kortsmit for her assistance with extracting data and assessing risk of bias for included studies.

1 Under contract with the Food and Nutrition Service, United States Department of Agriculture.