# References

1 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery (p. 3) https://store.samhsa.gov/sites/default/fíles/d7/priv/pep12-recdef.pdf.
2 Substance Abuse and Mental Health Services Administration. (2022). Recovery and recovery support. https://www.samhsa.gov/find-help/recovery.
3 Ignaszewski, M. J. (2021). The epidemiology of drug abuse. Journal of Clinical Pharmacology, 61(Suppl. 2), S10–S17.34396554
4 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
5 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
6 Han, B., Compton, W. M., Jones, C. M., Einstein, E. B., & Volkow, N. D. (2021). Methamphetamine use, methamphetamine use disorder, and associated overdose deaths among US adults. JAMA Psychiatry, 78(12), 1329–1342.34550301
7 National Institute on Drug Abuse. (2023, February 9). Drug overdose death rates. https://nida.nih.gov/research-topics/trends-statistics/overdose-death-rates.
8 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem [Discussion paper]. NAM Perspectives, 2021, 10.3147/202104b.
9 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services. https://addiction.surgeongeneral.gov/sites/default/files/surgeon-generals-report.pdf.
10 Davidson, L., Rowe, M., DiLeo, P., Bellamy, C., & Delphin-Rittmon, M. (2021). Recovery-oriented systems of care: A perspective on the past, present, and future. Alcohol Research: Current Reviews, 41(1), 09.34377618
11 Substance Abuse and Mental Health Services Administration. (2017). Peer support. https://www.samhsa.gov/sites/default/files/programs_campaigns/brss_tacs/peer-support-2017.pdf.
12 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. https://store.samhsa.gov/sites/default/files/d7/priv/pep12-recdef.pdf.
13 American Psychiatric Association. (2022). Diagnostic and statistical manual of mental disorders (5th ed., text revision). American Psychiatric Publishing.
14 American Psychiatric Association. (2022). Diagnostic and statistical manual of mental disorders (5th ed., text revision). American Psychiatric Publishing.
15 American Psychiatric Association. (2022). Diagnostic and statistical manual of mental disorders (5th ed., text revision). American Psychiatric Publishing.
16 Substance Abuse and Mental Health Services Administration. (2010). Recovery-oriented systems of care (ROSC) resource guide. Substance Abuse and Mental Health Services Administration.
17 Substance Abuse and Mental Health Services Administration. (2012). Building bridges: People in recovery from addictions and mental health problems in dialogue. HHS Publication No. (SMA) 12-4680. Substance Abuse and Mental Health Services Administration.
18 Nerlich, A. P., Landon, T J., & Keegan, J. P. (2022). A vision for rehabilitation counseling: Appreciative inquiry through the eyes of our legacy leaders. Rehabilitation Counselors and Educators Journal, 31744.
19 Kelly, J. F., Bergman, B., Hoeppner, B. B., Vilsaint, C., & White, W. L. (2017). Prevalence and pathways of recovery from drug and alcohol problems in the United States population: Implications for practice, research, and policy. Drug and Alcohol Dependence, 181, 162–169.29055821
20 Kelly, J. F., Abry, A. W., Milligan, C. M., Bergman, B. G., & Hoeppner, B. B. (2018). On being “in recovery”: A national study of prevalence and correlates of adopting or not adopting a recovery identity among individuals resolving drug and alcohol problems. Psychology of Addictive Behaviors, 32(6), 595–604.30070538
21 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. Publication ID: PEP12-RECDEF. Substance Abuse and Mental Health Services Administration.
22 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. Publication ID: PEP12-RECDEF. Substance Abuse and Mental Health Services Administration.
23 Substance Abuse and Mental Health Services Administration. (2012). Building bridges: People in recovery from addictions and mental health problems in dialogue. HHS Publication No. (SMA) 12-4680. Substance Abuse and Mental Health Services Administration.
24 Substance Abuse and Mental Health Services Administration. (2010). Recovery-oriented systems of care (ROSC) resource guide. Substance Abuse and Mental Health Services Administration.
25 Substance Abuse and Mental Health Services Administration. (2012). Building bridges: People in recovery from addictions and mental health problems in dialogue. HHS Publication No. (SMA) 12-4680. Substance Abuse and Mental Health Services Administration.
26 Kaskutas, L. A., Borkman, T. J., Laudet, A., Ritter, L. A., Witbrodt, J., Subbaraman, M. S., … Bond, J. (2014). Elements that define recovery: The experiential perspective. Journal of Studies on Alcohol and Drugs, 75(6), 999–1010.25343658
27 Kelly, J. F., Abry, A. W., Milligan, C. M., Bergman, B. G., & Hoeppner, B. B. (2018). On being “in recovery”: A national study of prevalence and correlates of adopting or not adopting a recovery identity among individuals resolving drug and alcohol problems. Psychology of Addictive Behaviors, 32(6), 595–604.30070538
28 Kelly, J. F., Abry, A. W., Milligan, C. M., Bergman, B. G., & Hoeppner, B. B. (2018). On being “in recovery”: A national study of prevalence and correlates of adopting or not adopting a recovery identity among individuals resolving drug and alcohol problems. Psychology of Addictive Behaviors, 32(6), 595–604.30070538
29 Pew Charitable Trusts. (2021). How licensed counselors could help address harmful substance use: Underutilized workforce could be leveraged to play critical role in prevention and treatment [Issue brief].
30 University of Michigan Behavioral Health Workforce Research Center. (2019). National analysis of peer support providers: Practice settings, requirements, roles, and reimbursement. University of Michigan School of Public Health.
31 Substance Abuse and Mental Health Services Administration. (2021). National Mental Health Services Survey (N-MHSS): 2020. Data on mental health treatment facilities. Substance Abuse and Mental Health Services Administration.
32 Ballard, S. C., & Bender, S. L. (2022). A systematic review of social, emotional, and behavioral interventions and outcomes for students in alternative education. Preventing School Failure: Alternative Education for Children and Youth, 66(2), 136–149.
33 Substance Abuse and Mental Health Services Administration. (2015). Screening and assessment of co-occurring disorders in the justice system. HHS Publication No. PEP19-SCREEN-CODJS. Substance Abuse and Mental Health Services Administration.
34 NASW Center for Workforce Studies & Social Work Practice. (2011). Social workers in social services agencies: Occupational profile. National Association of Social Workers. https://ncwwi.org/files/Job_Analysis_Position_Requirements/Social_Workers_in_Social_Services_Agencies_Occupational_Profile.pdf.
35 Nerlich, A. P., Landon, T J., & Keegan, J. P. (2022). A vision for rehabilitation counseling: Appreciative inquiry through the eyes of our legacy leaders. Rehabilitation Counselors and Educators Journal, 31744.
36 Isvan, N., Gerber, R., Hughes, D., Battis, K., Anderson, E., & O'Brien, J. (2019). Credentialing, licensing, and reimbursement of the SUD workforce: A review of policies and practices across the nation. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation, Office of Disability, Aging, and Long-Term Care Policy.
37 Page, C., Beck, A. J., Buche, J., Singer, P.M., Vazquez, C., & Perron, B. (2017). National assessment of scopes of practice for the behavioral health workforce. University of Michigan School of Public Health, Behavioral Health Workforce Research Center.
38 Stanojlovic, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
39 Watson, D. P., Brucker, K., McGuire, A., Snow-Hill, N. L., Xu, H., Cohen, A., … Kline, J. A. (2020). Replication of an emergency department-based recovery coaching intervention and pilot testing of pragmatic trial protocols within the context of Indiana's Opioid State Targeted Response plan. Journal of Substance Abuse Treatment, 108, 88–94.31200985
40 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
41 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
42 Centers for Disease Control and Prevention, National Center for Health Statistics. (2022, May 11). U.S. overdose deaths in 2021 increased half as much as in 2020 — But are still up 15% [Press release], https://www.cdc.gov/nchs/pressroom/nchs_press_releases/2022/202205.htm.
43 Centers for Disease Control and Prevention, National Center for Health Statistics. (2022, May 11). U.S. overdose deaths in 2021 increased half as much as in 2020 — But are still up 15% [Press release]. https://www.cdc.gov/nchs/pressroom/nchs_press_releases/2022/202205.htm.
44 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
45 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
46 Ellis, M. S., Kasper, Z. A., & Scroggins, S (2021). Shifting pathways of stimulant use among individuals with opioid use disorder: A retrospective analysis of the last thirty years. Frontiers in Psychiatry, 12, 2396.
47 Jones, C. M., Noonan, R. K., & Compton, W. M. (2020). Prevalence and correlates of ever having a substance use problem and substance use recovery status among adults in the United States, 2018. Drug and Alcohol Dependence, 214, 108169.32682218
48 Kelly, J. F., Greene, M. C., Bergman, B. G., White, W. L., & Hoeppner, B. B. (2019). How many recovery attempts does it take to successfully resolve an alcohol or drug problem? Estimates and correlates from a national study of recovering U.S. adults. Alcoholism: Clinical and Experimental Research, 43(7), 1533–1544.31090945
49 Substance Abuse and Mental Health Services Administration. (2022). National Substance Use and Mental Health Services Survey (N-SUMHSS), 2021: Data on substance use and mental health treatment facilities. HHS Publication No. PEP23-07-00-001. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
50 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health (Figure 56). HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
51 U.S. Department of Health and Human Services, Assistant Secretary for Planning and Evaluation, Behavioral Health, Disability, and Aging Policy. (2020). Understanding substance use disorder (SUD) treatment needs using assessment data: Final report..
52 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem. NAM Perspectives, 2021, 10.3147/202104b.
53 American Association for Community Psychiatry. (n.d.). LOCUS: Level of care utilization system for psychiatric and addiction services. https://www.communitypsychiatry.org/keystone-programs/locus.
54 Center for Mental Health Services. (2020). National guidelines for behavioral health crisis care best practice toolkit. Substance Abuse and Mental Health Services Administration.
55 American Association for Community Psychiatry. (n.d.). LOCUS: Level of care utilization system for psychiatric and addiction services. https://www.communitypsychiatry.org/keystone-programs/locus.
56 Kelly, J. F., Bergman, B., Hoeppner, B. B., Vilsaint, C., & White, W. L. (2017). Prevalence and pathways of recovery from drug and alcohol problems in the United States population: Implications for practice, research, and policy. Drug and Alcohol Dependence, 181, 1862–1869.
57 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
58 North America Syringe Exchange Network. (n.d.). SSP locations. Retrieved January 20, 2023, from https://nasen.org/map/.
59 Centers for Disease Control and Prevention, National Center for HIV, Viral Hepatitis, STD, and TB Prevention. (n.d.). Summary of information on the safety and effectiveness of syringe services programs (SSPs). https://www.cdc.gov/ssp/syringe-services-programs-summary.html.
60 Bloomberg American Health Initiative. (2018). Fentanyl Overdose Reduction Checking Analysis Study: FORECAST. Johns Hopkins Bloomberg School of Public Health.
61 Park, J. N., Frankel, S., Morris, M., Dieni, O., Fahey-Morrison, L., Luta, M., … Sherman, S. G. (2021). Evaluation of fentanyl test strip distribution in two Mid-Atlantic syringe services programs. International Journal on Drug Policy, 94, 103196.33713964
62 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
63 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
64 Heilig, M., MacKillop, J., Martinez, D., Rehm, J., Leggio, L., & Vanderschuren, L. (2021). Addiction as a brain disease revised: Why it still matters, and the need for consilience. Neuropsychopharmacology, 46(10), 1715–1723.33619327
65 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
66 Heilig, M., MacKillop, J., Martinez, D., Rehm, J., Leggio, L., & Vanderschuren, L. (2021). Addiction as a brain disease revised: Why it still matters, and the need for consilience. Neuropsychopharmacology, 46(10), 1715–1723.33619327
67 Heilig, M., MacKillop, J., Martinez, D., Rehm, J., Leggio, L., & Vanderschuren, L. (2021). Addiction as a brain disease revised: Why it still matters, and the need for consilience. Neuropsychopharmacology, 46(10), 1715–1723.33619327
68 Witkiewitz, K., Litten, R. Z., & Leggio, L. (2019). Advances in the science and treatment of alcohol use disorder. Science Advances, 5(9), eaax4043.31579824
69 Witkiewitz, K., Montes, K. S., Schwebel, F. J., & Tucker, J. A. (2020). What is recovery? Alcohol Research: Current Reviews, 40(3).
70 Acuff, S. F., Tucker, J. A., Vuchinich, R. E., & Murphy, J. G. (2022). Addiction is not (only) in the brain: Molar behavioral economic models of etiology and cessation of harmful substance use. In N. Heather, M. Field, A. C. Moss, & S. Satel (Eds.), Evaluating the brain disease model of addiction (pp. 459–474). Routledge.
71 Heilig, M., MacKillop, J., Martinez, D., Rehm, J., Leggio, L., & Vanderschuren, L. (2021). Addiction as a brain disease revised: Why it still matters, and the need for consilience. Neuropsychopharmacology, 46(10), 1715–1723.33619327
72 Witkiewitz, K., Litten, R. Z., & Leggio, L. (2019). Advances in the science and treatment of alcohol use disorder. Science Advances, 5(9), eaax4043.31579824
73 Skewes, M. C., & Gonzalez, V. M. (2013). The biopsychosocial model of addiction. In A. W. Blume, D. J. Kavanagh, K. M. Kampman, M. E. Bates, M. E. Larimer, N. M. Petry, P. De Witte, & S. A. Ball (Eds.), Principles of addiction: Vol. 1. Comprehensive addictive behaviors and disorders (pp. 61–70). Elsevier.
74 Kimball, T. G., Shumway, S. T., Bradshaw, S. D., & Soloski, K. L. (2020). A systemic understanding of addiction formation and the recovery process. In K. S. Wampler, M. Rastogi, & R. Singh (Eds.), The handbook of systemic family therapy: Vol. 4. Systematic family therapy and global health issues (pp. 325–355). Wiley.
75 Giordano, G. M., Brando, F., Pezzella, P., De Angelis, M., Mucci, A., & Galderisi, S. (2022). Factors influencing the outcome of integrated therapy approach in schizophrenia: A narrative review of the literature. Frontiers in Psychiatry, 1975.
76 Cohen, S. P., Vase, L., & Hooten, W. M. (2021). Chronic pain: An update on burden, best practices, and new advances. Lancet, 397(10289), 2082–2097.34062143
77 Nicholas, M. K. (2022). The biopsychosocial model of pain 40 years on: Time for a reappraisal? Pain, 163(Suppl. 1), S3–S14.36252231
78 Kimball, T. G., Shumway, S. T., Bradshaw, S. D., & Soloski, K. L. (2020). A systemic understanding of addiction formation and the recovery process. In K. S. Wampler, M. Rastogi, & R. Singh (Eds.), The handbook of systemic family therapy: Vol. 4. Systematic family therapy and global health issues (pp. 325–355). Wiley.
79 Mitchell, M. R., & Potenza, M. N. (2014). Addictions and personality traits: Impulsivity and related constructs. Current Behavioral Neuroscience Reports, 1(1), 1–12.24772382
80 Zilberman, N., Yadid, G., Efrati, Y., & Rassovsky, Y. (2020). Who becomes addicted and to what? Psychosocial predictors of substance and behavioral addictive disorders. Psychiatry Research, 291, 113221.32562935
81 Skewes, M. C., & Gonzalez, V. M. (2013). The biopsychosocial model of addiction. In A. W. Blume, D. J. Kavanagh, K. M. Kampman, M. E. Bates, M. E. Larimer, N. M. Petry, P. De Witte, & S. A. Ball (Eds.), Principles of addiction: Vol. 1. Comprehensive addictive behaviors and disorders (pp. 61–70). Elsevier.
82 Skewes, M. C., & Gonzalez, V. M. (2013). The biopsychosocial model of addiction. In A. W. Blume, D. J. Kavanagh, K. M. Kampman, M. E. Bates, M. E. Larimer, N. M. Petry, P. De Witte, & S. A. Ball (Eds.), Principles of addiction: Vol. 1. Comprehensive addictive behaviors and disorders (pp. 61–70). Elsevier.
83 Kimball, T. G., Shumway, S. T., Bradshaw, S. D., & Soloski, K. L. (2020). A systemic understanding of addiction formation and the recovery process. In K. S. Wampler, M. Rastogi, & R. Singh (Eds.), The handbook of systemic family therapy: Vol. 4. Systematic family therapy and global health issues (pp. 325–355). Wiley.
84 Skewes, M. C., & Gonzalez, V. M. (2013). The biopsychosocial model of addiction. In A. W. Blume, D. J. Kavanagh, K. M. Kampman, M. E. Bates, M. E. Larimer, N. M. Petry, P. De Witte, & S. A. Ball (Eds.), Principles of addiction: Vol. 1. Comprehensive addictive behaviors and disorders (pp. 61–70). Elsevier.
85 Ewald, D. R., Strack, R. W., & Orsini, M. M. (2019). Rethinking addiction. Global Pediatric Health, 6, 2333794X18821943.
86 Centers for Disease Control and Prevention, Division of Nutrition, Physical Activity, and Obesity. (n.d.). The built environment assessment tool manual. https://www.cdc.gov/nccdphp/dnpao/state-local-programs/built-environment-assessment/index.htm.
87 Barnett, A. I., Hall, W., Fry, C. L., Dilkes-Frayne, E., & Carter, A. (2018). Drug and alcohol treatment providers' views about the disease model of addiction and its impact on clinical practice: A systematic review. Drug and Alcohol Review, 37(6), 697–720.29239048
88 Volkow, N. D., Koob, G. F., & McLellan, A. T. (2016). Neurobiologie advances from the brain disease model of addiction. New England Journal of Medicine, 374(4), 363–371.26816013
89 Volkow, N. D., Koob, G. F., & McLellan, A. T. (2016). Neurobiologie advances from the brain disease model of addiction. New England Journal of Medicine, 374(4), 363–371.26816013
90 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
91 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
92 White, W., Kelly, J., & Roth, J. (2012). New addiction recovery support institutions: Mobilizing support beyond professional addiction treatment and recovery mutual aid. Journal of Groups in Addiction & Recovery, 7(2-4), 297–317.
93 Best, D., De Alwis, S. J., & Burdett, D. (2017). The recovery movement and its implications for policy, commissioning and practice. Nordic Studies on Alcohol and Drugs, 34(2), 107–111.
94 Substance Abuse and Mental Health Services Administration. (2012). Building bridges: People in recovery from addictions and mental health problems in dialogue. HHS Publication No. (SMA) 12-4680. Substance Abuse and Mental Health Services Administration.
95 Gumbley, S. (2016). Recovery in the 21st century: From shame to strength. Journal of Addictions Nursing, 27(2), 143–147.27272998
96 Ersche, K. D., Meng, C., Ziauddeen, H., Stochl, J., Williams, G. B., Bullmore, E. T., & Robbins, T. W. (2019). Brain networks underlying vulnerability and resilience to drug addiction. Proceedings of the National Academy of Sciences of the United States of America, 117(26), 15253–15261.
97 Moeller, S. J., & Paulus, M. P. (2018). Toward biomarkers of the addicted human brain: Using neuroimaging to predict relapse and sustained abstinence in substance use disorder. Progress in Neuro-Psychopharmacology and Biological Psychiatry, 80(Pt. B), 143–154.28322982
98 Klugah-Brown, B., Di, X., Zweerings, J., Mathiak, K., Becker, B., & Biswal, B. (2020). Common and separable neural alterations in substance use disorders: A coordinate-based meta-analyses of functional neuroimaging studies in humans. Human Brain Mapping, 41(16), 4459–4477.32964613
99 Deak, J. D., & Johnson, E. C. (2021). Genetics of substance use disorders: A review. Psychological Medicine, 51(13), 2189–2200.33879270
100 Demontis, D., Rajagopal, V. M., Thorgeirsson, T. E., Als, T. D., Grove, J., Leppälä, K., … Børglum, A. D. (2019). Genome-wide association study implicates CHRNA2 in cannabis use disorder. Nature Neuroscience, 22(7), 1066–1074.31209380
101 Egervari, G., Ciccocioppo, R., Jentsch, J. D., & Hurd, Y. L. (2018). Shaping vulnerability to addiction—The contribution of behavior, neural circuits and molecular mechanisms. Neuroscience & Biobehavioral Reviews, 85, 117–125.28571877
102 National Institute on Drug Abuse. (2019, August). Genetics and epigenetics of addiction DrugFacts. https://nida.nih.gov/publications/drugfacts/genetics-epigenetics-addiction.
103 MedlinePlus. (2022). What are single nucleotide polymorphisms (SNPs)? https://medlineplus.gov/genetics/understanding/genomicresearch/snp/.
104 Johnson, E. C., Chang, Y., & Agrawal, A. (2020). An update on the role of common genetic variation underlying substance use disorders. Current Genetic Medicine Reports, 8(2), 35–46.33457110
105 Johnson, E. C., Demontis, D., Thorgeirsson, T. E., Walters, R. K., Polimanti, R., Hatoum, A. S., … Agrawal, A. (2020). A large-scale genome-wide association study meta-analysis of cannabis use disorder. Lancet Psychiatry, 7(12), 1032–1045.33096046
106 Demontis, D., Rajagopal, V. M., Thorgeirsson, T E., Als, T D., Grove, J., Leppälä, K., … Børglum, A. D. (2019). Genome-wide association study implicates CHRNA2 in cannabis use disorder. Nature Neuroscience, 22(7), 1066–1074.31209380
107 National Human Genome Research Institute. (2020). Genome-wide association studies fact sheet. https://www.genome.gov/about-genomics/fact-sheets/Genome-Wide-Association-Studies-Fact-Sheet.
108 MedlinePlus. (2021). What is epigenetics? https://medlineplus.gov/genetics/understanding/howgeneswork/epigenome/.
109 MedlinePlus. (2021). What is epigenetics? https://medlineplus.gov/genetics/understanding/howgeneswork/epigenome/.
110 Baratta, A. M., Rathod, R. S., Plasil, S. L., Seth, A., & Homanics, G. E. (2021). Exposure to drugs of abuse induce effects that persist across generations. International Review of Neurobiology, 156, 217–277.33461664
111 Salgado, S., & Kaplitt, M. G. (2015). The nucleus accumbens: A comprehensive review. Stereotactic and Functional Neurosurgery, 93(2), 75–93.25720819
112 Baratta, A. M., Rathod, R. S., Plasil, S. L., Seth, A., & Homanics, G. E. (2021). Exposure to drugs of abuse induce effects that persist across generations. International Review of Neurobiology, 156, 217–277.33461664
113 Wanner, N. M., Colwell, M. L., & Faulk, C. (2019). The epigenetic legacy of illicit drugs: Developmental exposures and late-life phenotypes. Environmental Epigenetics, 5(4), dvz022.31777665
114 Szutorisz, H., & Hurd, Y L. (2022, April 11). Overcoming addiction stigma: Epigenetic contributions to substance use disorders and opportunities for intervention. Neuron, S0896-6273(22)00254-9. Advance online publication. https://doi.org/10.1016/j.neuron.2022.03.018.
115 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. https://store.samhsa.gov/sites/default/files/d7/priv/sma14-4884.pdf.
116 Substance Abuse and Mental Health Services Administration. (2018). National Strategy for Trauma-Informed Care Operating Plan. https://www.samhsa.gov/sites/default/fíles/trauma-informed-care-operating-plan.pdf.
117 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. https://store.samhsa.gov/sites/default/files/d7/priv/sma14-4884.pdf.
118 Substance Abuse and Mental Health Services Administration. (2018). National Strategy for Trauma-Informed Care Operating Plan. https://www.samhsa.gov/sites/default/fíles/trauma-informed-care-operating-plan.pdf.
119 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
120 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
121 Ross, S. L., Sharma-Patel, K., Brown, E. J., Huntt, J. S., & Chaplin, W. F. (2021). Complex trauma and trauma-focused cognitive-behavioral therapy: How do trauma chronicity and PTSD presentation affect treatment outcome?. Child Abuse & Neglect, 111, 104734.33162104
122 Substance Abuse and Mental Health Services Administration. (2022, September 27). Trauma and violence. https://www.samhsa.gov/trauma-violence.
123 Larbi, E. A., Berendzen, H. M., Smith, D. A., Anderson, S. C., & Roary, M. (2022, July 27). Coping with community violence together. https://www.samhsa.gov/blog/coping-community-violence-together.
124 Substance Abuse and Mental Health Services Administration. (2009). Addressing the specific needs of women. Treatment Improvement Protocol (TIP) Series 51. HHS Publication No. (SMA) 13-4426. Substance Abuse and Mental Health Services Administration.
125 Substance Abuse and Mental Health Services Administration. (2022, September 27). Trauma and violence. https://www.samhsa.gov/trauma-violence.
126 Centers for Disease Control and Prevention. (2019). Adverse childhood experiences (ACEs). Preventing early trauma to improve adult health. CDC Vitalsigns.™ https://www.cdc.gov/vitalsigns/aces/pdf/vs-1105-aces-H.pdf.
127 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
128 Centers for Disease Control and Prevention. (2019). Adverse childhood experiences (ACEs). Preventing early trauma to improve adult health. CDC Vitalsigns.™ https://www.cdc.gov/vitalsigns/aces/pdf/vs-1105-aces-H.pdf.
129 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
130 Chandler, G. E., Kalmakis, K. A., & Murtha, T. (2018). Screening adults with substance use disorder for adverse childhood experiences. Journal of Addictions Nursing, 29(3), 172–178.30180003
131 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
132 Chandler, G. E., Kalmakis, K. A., & Murtha, T. (2018). Screening adults with substance use disorder for adverse childhood experiences. Journal of Addictions Nursing, 29(3), 172–178.30180003
133 Petruccelli, K., Davis, J., & Berman, T (2019). Adverse childhood experiences and associated health outcomes: A systematic review and meta-analysis. Child Abuse and Neglect, 97, 104127.31454589
134 Hughes, K., Bellis, M. A., Hardcastle, K. A., Sethi, D., Butchart, A., Mikton, C., … Dunne, M. P. (2017). The effect of multiple adverse childhood experiences on health: A systematic review and meta-analysis. Lancet. Public Health, 2(8), e356–e366.29253477
135 Villamil Grest, C., Cederbaum, J. A., Lee, J. O., & Unger, J. B. (2021). Adverse childhood experiences and the substance use behaviors of Latinx youth. Drug and Alcohol Dependence, 227, 108936.34365223
136 Leza, L., Siria, S., López-Goñi, J. J., & Fernández-Montalvo, J. (2021). Adverse childhood experiences (ACEs) and substance use disorder (SUD): A scoping review. Drug and Alcohol Dependence, 221, 108563.33561668
137 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
138 Swedo, E. A., Sumner, S. A., de Fijter, S., Werhan, L., Norris, K., Beauregard, J. L., … Massetti, G. M. (2020). Adolescent opioid misuse attributable to adverse childhood experiences. Journal of Pediatrics, 224, 102–109.e3.32437756
139 Chandler, G. E., Kalmakis, K. A., & Murtha, T (2018). Screening adults with substance use disorder for adverse childhood experiences. Journal of Addictions Nursing, 29(3), 172–178.30180003
140 Cerdeña, J. P., Rivera, L. M., & Spak, J. M. (2021). Intergenerational trauma in Latinxs: A scoping review. Social Science & Medicine, 270, 113662.33476987
141 Gameon, J. A., & Skewes, M. C. (2021). Historical trauma and substance use among American Indian people with current substance use problems. Psychology of Addictive Behaviors, 35(3), 295–309.33829816
142 Jackson, L., Jackson, Z., & Jackson, F. (2018). Intergenerational resilience in response to the stress and trauma of enslavement and chronic exposure to institutionalized racism. Journal of Clinical Epigenetics, 4(3), 15.
143 Wilkins, E. J., Whiting, J. B., Watson, M. F., Russon, J. M., & Moncrief, A. M. (2013). Residual effects of slavery: What clinicians need to know. Contemporary Family Therapy, 35(1), 14–28.
144 Lee, A. T., Chin, P., Nambiar, A., & Hill Haskins, N. (2023). Addressing intergenerational trauma in Black families: Trauma-informed socio-culturally attuned family therapy. Journal of Marital and Family Therapy. Advance online publication. doi:10.1111/jmft.12632.
145 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
146 Vanderzee, K. L., John, S. G., Edge, N., Pemberton, J. R., & Kramer, T. L. (2017). A preliminary evaluation of the Managing Youth Trauma Effectively program for substance-abusing women and their children. Infant Mental Health Journal, 38(3), 422–433.28464299
147 Cerdeña, J. P., Rivera, L. M., & Spak, J. M. (2021). Intergenerational trauma in Latinxs: A scoping review. Social Science & Medicine, 270, 113662.33476987
148 Wang, X., Lee, M. Y., & Quinn, C. R. (2022). Intergenerational transmission of trauma: Unpacking the effects of parental adverse childhood experiences. Journal of Family Studies, 1–17.
149 Svingen, L., Dykstra, R. E., Simpson, J. L., Jaffe, A. E., Bevins, R. A., Carlo, G., … Grant, K. M. (2016). Associations between family history of substance use, childhood trauma, and age of first drug use in persons with methamphetamine dependence. Journal of Addiction Medicine, 10(4), 269–273.27427901
150 Svingen, L., Dykstra, R. E., Simpson, J. L., Jaffe, A. E., Bevins, R. A., Carlo, G., … Grant, K. M. (2016). Associations between family history of substance use, childhood trauma, and age of first drug use in persons with methamphetamine dependence. Journal of Addiction Medicine, 10(4), 269–273.27427901
151 Meulewaeter, F., De Pauw, S. S. W., & Vanderplasschen, W. (2019). Mothering, substance use disorders and intergenerational trauma transmission: An attachment-based perspective. Frontiers in Psychiatry, 10, 728.31681040
152 Skewes, M. C., & Blume, A. W. (2019). Understanding the link between racial trauma and substance use among American Indians. American Psychologist, 74(1), 88–100.30652902
153 Zapolski, T C. B., Rowe, A. T., Clifton, R. L., Khazvand, S., Crichlow, Q. J., & Faidley, M. (2021, December 23). Examining the unique and additive effect of trauma and racial microaggressions on substance use risk among Black young adults. Cultural Diversity and Ethnic Minority Psychology. Advance online publication. doi:10.1037/cdp0000480.
154 Skewes, M. C., & Blume, A. W. (2019). Understanding the link between racial trauma and substance use among American Indians. American Psychologist, 74(1), 88–100.30652902
155 Skewes, M. C., & Blume, A. W. (2019). Understanding the link between racial trauma and substance use among American Indians. American Psychologist, 74(1), 88–100.30652902
156 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 14-4816. Substance Abuse and Mental Health Services Administration.
157 Parekh, R., Al-Mateen, C. S., Lisotto, M. J., & Carter, R. D. (Eds.). (2020). Cultural psychiatry with children, adolescents, and families. American Psychiatric Association Publishing.
158 Dowling, B. A., Grigsby, T. J., Ziomek, G. J., & Schnarrs, P. W. (2022). Substance use outcomes for sexual and gender minority adults with a history of adverse childhood experiences: A scoping review. Drug and Alcohol Dependence Reports, 6, 100129.36994375
159 Dowling, B. A., Grigsby, T. J., Ziomek, G. J., & Schnarrs, P. W. (2022). Substance use outcomes for sexual and gender minority adults with a history of adverse childhood experiences: A scoping review. Drug and Alcohol Dependence Reports, 6, 100129.36994375
160 Parent, M. C., Arriaga, A. S., Gobble, T., & Wille, L. (2018). Stress and substance use among sexual and gender minority individuals across the lifespan. Neurobiology of Stress, 10, 100146.30937352
161 Dowling, B. A., Grigsby, T. J., Ziomek, G. J., & Schnarrs, P. W. (2022). Substance use outcomes for sexual and gender minority adults with a history of adverse childhood experiences: A scoping review. Drug and Alcohol Dependence Reports, 6, 100129.36994375
162 Parent, M. C., Arriaga, A. S., Gobble, T., & Wille, L. (2018). Stress and substance use among sexual and gender minority individuals across the lifespan. Neurobiology of Stress, 10, 100146.30937352
163 Yehuda, R., & Lehrner, A. (2018). Intergenerational transmission of trauma effects: Putative role of epigenetic mechanisms. World Psychiatry, 17(3), 243–257.30192087
164 Chan, J. C., Nugent, B. M., & Bale, T. L. (2018). Parental advisory: Maternal and paternal stress can impact offspring neurodevelopment. Biological Psychiatry, 83(10), 886–894.29198470
165 Thumfart, K. M., Jawaid, A., Bright, K., Flachsmann, M., & Mansuy, I. M. (2022). Epigenetics of childhood trauma: Long term sequelae and potential for treatment. Neuroscience and Biobehavioral Reviews, 132, 1049–1066.34742726
166 Chan, J. C., Nugent, B. M., & Bale, T. L. (2018). Parental advisory: Maternal and paternal stress can impact offspring neurodevelopment. Biological Psychiatry, 83(10), 886–894.29198470
167 Thumfart, K. M., Jawaid, A., Bright, K., Flachsmann, M., & Mansuy, I. M. (2022). Epigenetics of childhood trauma: Long term sequelae and potential for treatment. Neuroscience and Biobehavioral Reviews, 132, 1049–1066.34742726
168 Centers for Disease Control and Prevention. (2021). Fast facts: Preventing intimate partner violence. https://www.cdc.gov/violenceprevention/intimatepartnerviolence/fastfact.html#:~:text=Intimate%20partner%20violence%20(IPV)%20isfand%20how%20severe%20it%20is.
169 Centers for Disease Control and Prevention. (2021). Fast facts: Preventing intimate partner violence. https://www.cdc.gov/violenceprevention/intimatepartnerviolence/fastfact.html#:~:text=Intimate%20partner%20violence%20(IPV)%20isfand%20how%20severe%20it%20is.
170 Smith, S. G., Zhang, X., Basile, K. C., Merrick, M. T., Wang, J., Kresnow, M., & Chen, J. (2018). The National Intimate Partner and Sexual Violence Survey (NISVS): 2015 data brief; Updated release. Centers for Disease Control and Prevention, National Center for Injury Prevention and Control.
171 Antebi-Gruszka, N., & Scheer, J. R. (2021). Associations between trauma-Informed care components and multiple health and psychosocial risks among LGBTQ survivors of intimate partner violence. Journal of Mental Health Counseling, 43(2), 139–156.34092983
172 Peitzmeier, S. M., Malik, M., Kattari, S. K., Marrow, E., Stephenson, R., Agénor, M., & Reisner, S. L. (2020). Intimate partner violence in transgender populations: Systematic review and meta-analysis of prevalence and correlates. American Journal of Public Health, 110(9), e1–e14.
173 Antebi-Gruszka, N., & Scheer, J. R. (2021). Associations between trauma-Informed care components and multiple health and psychosocial risks among LGBTQ survivors of intimate partner violence. Journal of Mental Health Counseling, 43(2), 139–156.34092983
174 Cafferky, B. M., Mendez, M., Anderson, J. R., & Stith, S. M. (2018). Substance use and intimate partner violence: A meta-analytic review. Psychology of Violence, 8(1), 110.
175 Cafferky, B. M., Mendez, M., Anderson, J. R., & Stith, S. M. (2018). Substance use and intimate partner violence: A meta-analytic review. Psychology of Violence, 8(1), 110.
176 Cafferky, B. M., Mendez, M., Anderson, J. R., & Stith, S. M. (2018). Substance use and intimate partner violence: A meta-analytic review. Psychology of Violence, 8(1), 110.
177 Phillips, H., Warshaw, C., & Kaewken, O. (2020). Literature review: Intimate partner violence, substance use coercion, and the need for integrated service models. National Center on Domestic Violence, Trauma, and Mental Health.
178 Warshaw, C., Lyon, E., Bland, P. J., Phillips, H., & Hooper, M. (2014). Mental health and substance use coercion surveys: Report from the National Center on Domestic Violence, Trauma & Mental Health and the National Domestic Violence Hotline (p. 12). National Center on Domestic Violence, Trauma & Mental Health; National Domestic Violence Hotline.
179 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. (n.d.). Social determinants of health. https://health.gov/healthypeople/priority-areas/social-determinants-health.
180 Park, J. N., Rouhani, S., Beletsky, L., Vincent, L., Saloner, B., & Sherman, S. G. (2020). Situating the continuum of overdose risk in the social determinants of health: A new conceptual framework. Milbank Quarterly, 98(3), 700–746.32808709
181 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. (n.d.). Social determinants of health. https://health.gov/healthypeople/priority-areas/social-determinants-health.
182 Gómez, C. A., Kleinman, D. V., Pronk, N., Wrenn Gordon, G. L., Ochiai, E., Blakey, C., … Brewer, K. H. (2021). Addressing health equity and social determinants of health through Healthy People 2030. Journal of Public Health Management and Practice, 27(Suppl. 6), S249–S257.33729197
183 Artiga, S., & Hinton, E. (2018). Beyond health care: The role of social determinants in promoting health and health equity. Kaiser Family Foundation. https://www.kff.org/racial-equity-and-health-policy/issue-brief/beyond-health-care-the-role-of-social-determinants-in-promoting-health-and-health-equity/.
184 U.S. Department of Health and Human Services, Office of Disease Prevention and Health Promotion. (n.d.). Social and community context. https://health.gov/healthypeople/objectives-and-data/browse-objectives/social-and-community-context.
185 Shokoohi, M., Bauer, G. R., Kaida, A., Logie, C. H., Lacombe-Duncan, A., Milloy, M. J., … Loutfy, M. (2019). Patterns of social determinants of health associated with drug use among women living with HIV in Canada: A latent class analysis. Addiction, 114(7), 1214–1224.30698902
186 Swan, J. E., Aldridge, A., Joseph, V., Tucker, J. A., & Witkiewitz, K. (2021). Individual and community social determinants of health and recovery from alcohol use disorder three years following treatment. Journal of Psychoactive Drugs, 53(5), 394–403.34727839
187 Swan, J. E., Aldridge, A., Joseph, V., Tucker, J. A., & Witkiewitz, K. (2021). Individual and community social determinants of health and recovery from alcohol use disorder three years following treatment. Journal of Psychoactive Drugs, 53(5), 394–403.34727839
188 Assari, S., Smith, J., Mistry, R., Farokhnia, M., & Bazargan, M. (2019). Substance use among economically disadvantaged African American older adults; Objective and subjective socioeconomic status. International Journal of Environmental Research and Public Health, 16(10), 1826.31126049
189 Cook, W. K., Mulia, M., & Libo, L. (2020). Subjective social status and financial hardship: Associations of alternative indicators of socioeconomic status with problem drinking in Asian Americans and Latinos, Substance Use and Misuse, 55(8), 1246–1256.32133915
190 Hollingsworth, A., Ruhm, C., & Simon, K. (2017). Macroeconomic conditions and opioid abuse. Journal of Health Economics, 56, 222–233.29128677
191 Azagba, S., Shan, L., Qeadan, F., & Wolfson, M. (2021). Unemployment rate, opioids misuse and other substance abuse: quasi-experimental evidence from treatment admissions data. BMC Psychiatry, 21(1), 22.33423671
192 Austin, A. E., Shiue, K. Y., Naumann, R. B., Figgatt, M. C., Gest, C., & Shanahan, M. E. (2021). Associations of housing stress with later substance use outcomes: A systematic review. Addictive Behaviors, 123, 107076.34385075
193 Altekruse, S. F., Cosgrove, C. M., Altekruse, W. C., Jenkins, R. A., & Blanco, C. (2020). Socioeconomic risk factors for fatal opioid overdoses in the United States: Findings from the Mortality Disparities in American Communities Study (MDAC). PloS One, 15(1), e0227966.31951640
194 Salas-Wright, C. P., Oh, S., Vaughn, M. G., Cohen, M., Scott, J. C., & Amodeo, M. (2019). Trends and drug-related correlates in residential mobility among young adults in the United States, 2003-2016. Addictive Behaviors, 90, 146–150.30396097
195 Shearer, R. D., Howell, B. A., Bart, G., & Winkelman, T N. (2020). Substance use patterns and health profiles among US adults who use opioids, methamphetamine, or both, 2015-2018. Drug and Alcohol Dependence, 214, 108162.32652380
196 Pettersen, H., Landheim, A., Skeie, I., Biong, S., Brodahl, M., Oute, J., & Davidson, L. (2019). How social relationships influence substance use disorder recovery: A collaborative narrative study. Substance Abuse: Research and Treatment, 13, 1178221819833379.30886519
197 Nicholson, H. L., Jr., & Ford, J. A. (2019). Sociodemographic, neighborhood, psychosocial, and substance use correlates of cocaine use among Black adults: Findings from a pooled analysis of national data. Addictive Behaviors, 88, 182–186.30218941
198 Nicholson, H. L., Jr., & Ford, J. A. (2019). Sociodemographic, neighborhood, psychosocial, and substance use correlates of cocaine use among Black adults: Findings from a pooled analysis of national data. Addictive Behaviors, 88, 182–186.30218941
199 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
200 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
201 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
202 Substance Abuse and Mental Health Services Administration. (2020). The opioid crisis and the Hispanic/Latino Population: An urgent Issue. Publication No. PEP20-05-02-002. Substance Abuse and Mental Health Services Administration, Office of Behavioral Health Equity.
203 Garcini, L. M., Murray, K. E., Zhou, A., Klonoff, E. A., Myers, M. G., & Elder, J. P. (2016). Mental health of undocumented immigrant adults in the United States: A systematic review of methodology and findings. Journal of Immigrant & Refugee Studies, 14(1), 1–25.
204 Pinedo, M., Montero-Zamora, P., Pasch, K. E., & Schwartz, S. J. (2022). Immigration policies as political determinants of alcohol and drug misuse among US-born Latinos. International Journal of Drug Policy, 106, 103754.35688060
205 Chichester, K., Drawve, G., Giménez-Santana, A., Sisson, M., McCleskey, B., Dye, D. W., … Cropsey, K. (2020). Pharmacies and features of the built environment associated with opioid overdose: A geospatial comparison of rural and urban regions in Alabama, USA. International Journal on Drug Policy, 79, 102736.32278255
206 Tempalski, B., Williams, L. D., Kolak, M., Ompad, D. C., Koschinsky, J., & McLafferty, S. L. (2022). Conceptualizing the socio-built environment: An expanded theoretical framework to promote a better understanding of risk for nonmedical opioid overdose outcomes in urban and non-urban settings (p. 705). Journal of Urban Health, 99, 701–716.35672547
207 Cerdá, M., Ransome, Y., Keyes, K. M., Koenen, K. C., Tardiff, K., Vlahov, D., & Galea, S. (2013). Revisiting the role of the urban environment in substance use: The case of analgesic overdose fatalities. American Journal of Public Health, 103(12), 2252–2260.24134362
208 Lee, E., & Santiago, A. M. (2021). Cumulative exposure to neighborhood conditions and substance use initiation among low-income Latinx and African American adolescents. International Journal of Environmental Research and Public Health, 18(20), 10831.34682576
209 Lee, E., & Santiago, A. M. (2021). Cumulative exposure to neighborhood conditions and substance use initiation among low-income Latinx and African American adolescents. International Journal of Environmental Research and Public Health, 18(20), 10831.34682576
210 Sistani, F., de Bittner, M. R., & Shaya, F. T. (2023). Social determinants of health, substance use, and drug overdose prevention. Journal of the American Pharmacists Association, 63(2), 628–632.36411231
211 Harwerth, J., Washburn, M., Lee, K., & Basham, R. E. (2022). Transportation barriers to outpatient substance use treatment programs: A scoping review. Journal of Evidence-Based Social Work, 20(2), 159–178.
212 Cook, W. K., Mulia, M., & Libo, L. (2020). Subjective social status and financial hardship: Associations of alternative indicators of socioeconomic status with problem drinking in Asian Americans and Latinos. Substance Use and Misuse, 55(8), 1246–1256.32133915
213 Morse, D. S., Cerulli, C., Hordes, M., El-Bassel, N., Bleasdale, J., Wilson, K., … Przybyla, S. M. (2022). “I was 15 when I started doing drugs with my dad”: Victimization, social determinants of health, and criminogenic risk among women opioid intervention court participants. Journal of Interpersonal Violence, 37, 21–22.
214 Hollingsworth, A., Ruhm, C., & Simon, K. (2017). Macroeconomic conditions and opioid abuse. Journal of Health Economics, 56, 222–233.29128677
215 Vilsaint, C. L., NeMoyer, A., Fillbrunn, M., Sadikova, E., Kessler, R. C., Sampson, N. A., … Alegría, M. (2019). Racial/ethnic differences in 12-month prevalence and persistence of mood, anxiety, and substance use disorders: Variation by nativity and socioeconomic status. Comprehensive Psychiatry, 89, 52–60.30594752
216 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
217 Acevedo, A., Panas, L., & Garnick, D. (2018). Disparities in the treatment of substance use disorders: Does where you live matter? Journal of Behavioral Health Services Research, 45, 533–549.29435862
218 Substance Abuse and Mental Health Services Administration. (2023, January 9). About the Office of Behavioral Health Equity. https://www.samhsa.gov/behavioral-health-equity/about.
219 Swendsen, J., Conway, K. P., Degenhardt, L., Glantz, M., Jin, R., Merikangas, K. R., … Kessler, R. C. (2010). Mental disorders as risk factors for substance use, abuse and dependence: Results from the 10-year follow-up of the National Comorbidity Survey. Addiction, 105, 1117–1128.20331554
220 Conway, K. P., Swendsen, J., Husky, M. M., He, J., & Merikangas, K. R. (2016). Association of lifetime mental disorders and subsequent alcohol and illicit drug use: Results from the National Comorbidity Survey-Adolescent Supplement. Journal of the American Academy of Child & Adolescent Psychiatry, 55(4), 280–288.27015718
221 National Institute on Drug Abuse. (2021). Why is there comorbidity between substance use disorders and mental illnesses? Common Comorbidities with Substance Use Disorders Research Report. https://nida.nih.gov/publications/research-reports/common-comorbidities-substance-use-disorders/why-there-comorbidity-between-substance-use-disorders-mental-illnesses.
222 Turner, S., Mota, N., Bolton, J., & Sareen, J. (2018). Self-medication with alcohol or drugs for mood and anxiety disorders: A narrative review of the epidemiological literature. Depression and Anxiety, 35(9), 851–860.29999576
223 Turner, S., Mota, N., Bolton, J., & Sareen, J. (2018). Self-medication with alcohol or drugs for mood and anxiety disorders: A narrative review of the epidemiological literature. Depression and Anxiety, 35(9), 851–860.29999576
224 National Institute on Drug Abuse. (2021). Why is there comorbidity between substance use disorders and mental illnesses? Common Comorbidities with Substance Use Disorders Research Report. https://nida.nih.gov/publications/research-reports/common-comorbidities-substance-use-disorders/why-there-comorbidity-between-substance-use-disorders-mental-illnesses.
225 National Institute on Drug Abuse. (2021). Why is there comorbidity between substance use disorders and mental illnesses? Common Comorbidities with Substance Use Disorders Research Report. https://nida.nih.gov/publications/research-reports/common-comorbidities-substance-use-disorders/why-there-comorbidity-between-substance-use-disorders-mental-illnesses.
226 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment for people with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. SAMHSA Publication No. PEP20-02-01-004. Substance Abuse and Mental Health Services Administration.
227 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem [Discussion paper]. NAM Perspectives, 2021, 10.3147/202104b.
228 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
229 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
230 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem [Discussion paper]. NAM Perspectives, 2021, 10.3147/202104b.
231 Funke, M., Kaplan, M. C., Glover, H., Schramm-Sapyta, N., Muzyk, A., Mando-Vandrick, J., … Eucker, S. A. (2021). Increasing naloxone prescribing in the emergency department through education and electronic medical record work-aids. Joint Commission Journal on Quality and Patient Safety, 47(6), 364–375.33811002
232 Hawk, K., & D'Onofrio, G. (2018). Emergency department screening and interventions for substance use disorders. Addiction Science and Clinical Practice, 13(1), 18.30078375
233 National Mental Health and Substance Use Policy Laboratory. (2021). Use of medication-assisted treatment in emergency departments. HHS Publication No. PEP21-PL-Guide-5. Substance Abuse and Mental Health Services Administration.
234 Suen, L. W., Makam, A. N., Snyder, H. R., Repplinger, D., Kushel, M. B., Martin, M., & Nguyen, O. K. (2022). National prevalence of alcohol and other substance use disorders among emergency department visits and hospitalizations: NHAMCS 2014-2018. Journal of General Internal Medicine, 37, 2420–2428.34518978
235 Hawk, K., & D'Onofrio, G. (2018). Emergency department screening and interventions for substance use disorders. Addiction Science and Clinical Practice, 13(1), 18.30078375
236 Hawk, K., & D'Onofrio, G. (2018). Emergency department screening and interventions for substance use disorders. Addiction Science and Clinical Practice, 13(1), 18.30078375
237 Hawk, K., Hoppe, J., Ketcham, E., LaPietra, A., Moulin, A., Nelson, L., … D'Onofrio, G. (2021). Consensus recommendations on the treatment of opioid use disorder in the emergency department. Annals of Emergency Medicine, 78(3), 434–442.34172303
238 Substance Abuse and Mental Health Services Administration. (2021). Use of medication-assisted treatment in emergency departments. HHS Publication No. PEP21-PL-Guide-5. Substance Abuse and Mental Health Services Administration, National Mental Health and Substance Use Policy Laboratory.
239 Philippine, T., Forsgren, E., DeWitt, C., Carter, I., McCollough, M., & Taira, B. R. (2022). Provider perspectives on emergency department initiation of medication assisted treatment for alcohol use disorder. BMC Health Services Research, 22(1), 456.35392901
240 Boss, R., Daly, B., & Sadwith, T (2020). Addressing substance use in behavioral health crisis care: A companion resource to the SAMHSA Crisis Toolkit. National Association of State Mental Health Program Directors.
241 Substance Abuse and Mental Health Services Administration. (2020). National guidelines for behavioral health crisis care: Best practice toolkit. Substance Abuse and Mental Health Services Administration.
242 National Association of State Mental Health Program Directors. (2020). Addressing substance use in behavioral health crisis care: A companion resource to the SAMHSA Crisis Toolkit (p. 21).
243 Substance Abuse and Mental Health Services Administration. (2023, March 23). 988 frequently asked questions. https://www.samhsa.gov/find-help/988/faqs.
244 Boss, R., Daly, B., & Sadwith, T (2020). Addressing substance use in behavioral health crisis care: A companion resource to the SAMHSA Crisis Toolkit. National Association of State Mental Health Program Directors.
245 Boss, R., Daly, B., & Sadwith, T (2020). Addressing substance use in behavioral health crisis care: A companion resource to the SAMHSA Crisis Toolkit. National Association of State Mental Health Program Directors.
246 Substance Abuse and Mental Health Services Administration. (2020). National guidelines for behavioral health crisis care: Best practice toolkit. Substance Abuse and Mental Health Services Administration.
247 Substance Abuse and Mental Health Services Administration. (2020). National guidelines for behavioral health crisis care: Best practice toolkit. Substance Abuse and Mental Health Services Administration.
248 Boss, R., Daly, B., & Sadwith, T. (2020). Addressing substance use in behavioral health crisis care: A companion resource to the SAMHSA Crisis Toolkit. National Association of State Mental Health Program Directors.
249 Champagne-Langabeer, T., Bakos-Block, C., Yatsco, A., & Langabeer, J. R. (2020). Emergency medical services targeting opioid user disorder: An exploration of current out-of-hospital postoverdose interventions. Journal of the American College of Emergency Physicians Open, 1(6), 1230–1239.33392528
250 Champagne-Langabeer, T., Bakos-Block, C., Yatsco, A., & Langabeer, J. R. (2020). Emergency medical services targeting opioid user disorder: An exploration of current out-of-hospital postoverdose interventions. Journal of the American College of Emergency Physicians Open, 1(6), 1230–1239.33392528
251 Ehrhart, J. (2020). How EMS can help reduce opioid abuse. EMS World. https://www.hmpgloballearningnetwork.com/site/emsworld/article/1223789/how-ems-can-help-reduce-opioid-abuse.
252 Clinical Info HIV.gov. (2021, June 3). Guidelines for the use of antiretroviral agents in adults and adolescents with HIV. https://clinicalinfo.hiv.gov/en/guidelines/adult-and-adolescent-arv/substance-use-disorders-and-hiv.
253 Strathdee, S. A., Bristow, C. C., Gaines, T., & Shoptaw, S. (2021). Collateral damage: A narrative review on epidemics of substance use disorders and their relationships to sexually transmitted infections in the United States. Sexually Transmitted Diseases, 48(7), 466.33315749
254 Marks, C., Carrasco-Escobar, G., Carrasco-Hernández, R., Johnson, D., Ciccarone, D., Strathdee, S. A., … Bórquez, A. (2021). Methodological approaches for the prediction of opioid use-related epidemics in the United States: A narrative review and cross-disciplinary call to action. Translational Research, 234, 88–113.33798764
255 Winetsky, D., Fox, A., Nijhawan, A., & Rich, J. D. (2020). Treating opioid use disorder and related infectious diseases in the criminal justice system. Infectious Disease Clinics, 34(3), 585–603.32782103
256 Bositis, C. M., & Louis, J. S. (2019). HIV and substance use disorder: Role of the HIV physician. Infectious Disease Clinics, 33(3), 835–855.31255382
257 Serota, D. P., Barocas, J. A., & Springer, S. A. (2020). Infectious complications of addiction: A call for a new subspecialty within infectious diseases. Clinical Infectious Diseases, 70(5), 968–972.31420651
258 Rapoport, A. B., Fischer, L. S., Santibanez, S., Beekmann, S. E., Polgreen, P. M., & Rowley, C. F. (2018). Infectious diseases physicians' perspectives regarding injection drug use and related infections, United States, 2017. Open Forum Infectious Diseases, 5(7), ofy132.30018999
259 NORC at the University of Chicago & Center for Health & Justice at TASC. (2021). Report of the National Survey to Assess Law Enforcement-led Diversion and First Responder Deflection Programs in Response to the Opioid Crisis: Final report. U.S. Department of Justice, Bureau of Justice Assistance, Comprehensive Opioid, Stimulant, and Substance Abuse Program.
260 NORC at the University of Chicago & Center for Health & Justice at TASC. (2021). Report of the National Survey to Assess Law Enforcement-led Diversion and First Responder Deflection Programs in Response to the Opioid Crisis: Final report. U.S. Department of Justice, Bureau of Justice Assistance, Comprehensive Opioid, Stimulant, and Substance Abuse Program.
261 Bureau of Justice Assistance, Comprehensive Opioid, Stimulant, and Substance Abuse Program. (2022). Jail diversion models: Part I (NCJ No: 304477). U.S. Department of Justice.
262 Spigt, M., & Scherrer, J. F. (2022). Family practice substance use disorder theme issue: Commentary. Family Practice, 39(2), 223–225.35134159
263 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
264 Steinberg, J., Azofeifa, A., & Sigounas, G. (2019). Mobilizing primary care to address the opioid use disorder treatment gap. Public Health Reports (Washington, D.C.), 134(5), 456–460.
265 U.S. Preventive Services Task Force, Krist, A. H., Davidson, K. W., Mangione, C. M., Barry, M. J., Cabana, M., … Wong, J. B. (2020). Screening for unhealthy drug use: U.S. Preventive Services Task Force Recommendation Statement. JAMA, 323(22), 2301–2309.32515821
266 McNeely, J., Kumar, P. C., Rieckmann, T., Sedlander, E., Farkas, S., Chollak, C., … Rotrosen, J. (2018). Barriers and facilitators affecting the implementation of substance use screening in primary care clinics: A qualitative study of patients, providers, and staff. Addiction Science & Clinical Practice, 13(1), 8.29628018
267 U.S. Preventive Services Task Force, Krist, A. H., Davidson, K. W., Mangione, C. M., Barry, M. J., Cabana, M., … Wong, J. B. (2020). Screening for unhealthy drug use: U.S. Preventive Services Task Force Recommendation Statement. JAMA, 323(22), 2301–2309.32515821
268 Townley, C., & Dorr, H. (2017). Integrating substance use disorder treatment and primary care. National Academy for State Health Policy.
269 Substance Abuse and Mental Health Services Administration. (2022). Coding for screening and brief intervention reimbursement. https://www.samhsa.gov/sbirt/coding-reimbursement.
270 Centers for Medicare & Medicaid Services. (2022). SBIRTservices (MLN904084). https://www.cms.gov/Outreach-and-Education/Medicare-Learning-Network-MLN/MLNProducts/downloads/sbirt_factsheet_icn904084.pdf.
271 Scott, C. K., Grella, C. E., Dennis, M. L., & Nicholson, L. (2018). Linking individuals with substance use disorders (SUDs) in primary care to SUD treatment: The recovery management checkups-primary care (RMC-PC) pilot study. Journal of Behavioral Health Services & Research, 45(2), 160–173.29181779
272 Scott, C. K., Dennis, M. L., Grella, C. E., Watson, D. P., Davis, J. P., & Hart, M. K. (2022, October 8). Using recovery management checkups for primary care to improve linkage to alcohol and other drug use treatment: A randomized controlled trial three month findings. Addiction (Abingdon, England). Advance online publication. doi:org/10.1111/add.16064.
273 Scott, C. (2022). Recovery management checkups for primary care experiment (RMC-PC). (ClinicalTrials.gov Identifier: NCT03746756). https://clinicaltrials.gov/ct2/show/NCT03746756.
274 Health and Human Services Department. (2021). Practice guidelines for the administration of buprenorphine for treating opioid use disorder. Federal Register. https://www.federalregister.gov/documents/2021/04/28/2021-08961/practice-guidelines-for-the-administration-of-buprenorphine-for-treating-opioid-use-disorder.
275 Substance Abuse and Mental Health Services Administration. (n.d.). Waiver elimination (MAT Act). Retrieved January 12, 2023, from https://www.samhsa.gov/medication-assisted-treatment/removal-data-waiver-requirement.
276 Substance Abuse and Mental Health Services Administration. (2021). Prescribing pharmacotherapies for patients with alcohol use disorder. Advisory. SAMHSA Publication No. PEP20-02-02-015. Substance Abuse and Mental Health Services Administration.
277 Korthuis, P. T., McCarty, D., Weimer, M., Bougatsos, C., Blazina, I., Zakher, B., … Chou, R. (2017). Primary care-based models for the treatment of opioid use disorder: A scoping review. Annals of Internal Medicine, 166(4), 268–278.27919103
278 Buresh, M., Stern, R., & Rastegar, D. (2021). Treatment of opioid use disorder in primary care. BMJ (Clinical Research Ed.), 373, n784.
279 Korthuis, P. T., McCarty, D., Weimer, M., Bougatsos, C., Blazina, I., Zakher, B., … Chou, R. (2017). Primary care-based models for the treatment of opioid use disorder: A scoping review. Annals of Internal Medicine, 166(4), 268–278.27919103
280 Townley, C., & Dorr, H. (2017). Integrating substance use disorder treatment and primary care. National Academy for State Health Policy.
281 McGinty, E. E., & Daumit, G. L. (2020). Integrating mental health and addiction treatment into general medical care: The role of policy. Psychiatric Services, 71(11), 1163–1169.32487007
282 McGinty, E. E., & Daumit, G. L. (2020). Integrating mental health and addiction treatment into general medical care: The role of policy. Psychiatric Services, 71(11), 1163–1169.32487007
283 O'Malley, D. M., Abraham, C. M., Lee, H. S., Rubinstein, E. B., Howard, J., Hudson, S. V., … Crabtree, B. F. (2022). Substance use disorder approaches in US primary care clinics with national reputations as workforce innovators. Family Practice, 39(2), 282–291.34423366
284 Stone, E. M., Kennedy-Hendricks, A., Barry, C. L., Bachhuber, M. A., & McGinty, E. E. (2021). The role of stigma in US primary care physicians' treatment of opioid use disorder. Drug and Alcohol Dependence, 221, 108627.33621805
285 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
286 Vogel, M. E., Kanzler, K. E., Aikens, J. E., & Goodie, J. L. (2017). Integration of behavioral health and primary care: Current knowledge and future directions. Journal of Behavioral Medicine, 40(1), 69–84.27696126
287 Lagisetty, P., Klasa, K., Bush, C., Heisler, M., Chopra, V., & Bohnert, A. (2017). Primary care models for treating opioid use disorders: What actually works? A systematic review. PloS One, 12(10), e0186315.29040331
288 Volk, J., Palanker, D., O'Brien, M., & Goe, C. (2021, June 23). States' actions to expand telemedicine access during COVID-19 and future policy considerations. [Issue brief]. Commonwealth Fund. https://www.commonwealthfund.org/publications/issue-briefs/2021/jun/states-actions-expand-telemedicine-access-covid-19.
289 Cantor, J., McBain, R. K., Kofner, A., Hanson, R., Stein, B. D., & Yu, H. (2022). Telehealth adoption by mental health and substance use disorder treatment facilities in the COVID-19 pandemic. Psychiatric Services (Washington, D.C.), 73(4), 411–417.34407631
290 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. Advisory. SAMHSA Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
291 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. Advisory. SAMHSA Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
292 Substance Abuse and Mental Health Services Administration. (2015). Using technology-based therapeutic tools in behavioral health services. Treatment Improvement Protocol (TIP) Series 60. HHS Publication No. (SMA) 15-4924. Substance Abuse and Mental Health Services Administration.
293 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. SAMHSA Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
294 Sugarman, D. E., Busch, A. B., McHugh, R. K., Bogunović, O. J., Trinh, C. D., Weiss, R. D., & Greenfield, S. F. (2021). Patients' perceptions of telehealth services for outpatient treatment of substance use disorders during the COVID-19 pandemic. American Journal on Addictions, 30(5), 445–452.34405475
295 Mark, T. L., Treiman, K., Padwa, H., Henretty, K., Tzeng, J., & Gilbert, M. (2022). Addiction treatment and telehealth: Review of efficacy and provider insights during the COVID-19 pandemic. Psychiatric Services, 73(5), 484–491.34644125
296 Ngo, Q. M., Braughton, J. E., Gliske, K., Waller, L. A., Sitar, S., Kretman, D. N., … Welsh, J. W. (2022). In-person versus telehealth setting for the delivery of substance use disorder treatment: Ecologically valid comparison study. JMIR Formative Research, 6(4), e34408.35377318
297 Mark, T. L., Treiman, K., Padwa, H., Henretty, K., Tzeng, J., & Gilbert, M. (2022). Addiction treatment and telehealth: Review of efficacy and provider insights during the COVID-19 pandemic. Psychiatric Services, 73(5), 484–491.34644125
298 Harper, L. M. (2021). Telehealth approaches to improve opioid use care in pregnancy. Clinical Obstetrics and Gynecology, 64(2), 352–365.33882519
299 Mark, T. L., Treiman, K., Padwa, H., Henretty, K., Tzeng, J., & Gilbert, M. (2021). Addiction treatment and telehealth: Review of efficacy and provider insights during the COVID-19 pandemic. Psychiatric Services, 73(5), 484–491.34644125
300 Brett, A., Foster, H., Joseph, M., & Warrington, J.S. (2021). Patient-centered telehealth solution for observed urine collections in substance use disorder care delivery during COVID-19 and beyond. Journal of Patient Experience, 8, 23743735211033128.34377769
301 Poulsen, M. N., Santoro, W., Scotti, R., Henderson, C., Ruddy, M., & Colistra, A. (2022, September 20). Implementation of telemedicine delivery of medications for opioid use disorder in Pennsylvania treatment programs during COVID-19. Journal of Addiction Medicine. Advance online publication. doi:10.1097/ADM.0000000000001079.
302 Sweeney, M. M., Holtyn, A. F., Stitzer, M. L., & Gastfriend, D. R. (2022). Practical technology for expanding and improving substance use disorder treatment: Telehealth, remote monitoring, and digital health interventions. Psychiatric Clinics of North America, 45(3), 515–528.36055736
303 Harper, L. M. (2021). Telehealth approaches to improve opioid use care in pregnancy. Clinical Obstetrics and Gynecology, 64(2), 352–365.33882519
304 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. Advisory. SAMHSA Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
305 Gallegos-Rejas, V. M., Thomas, E. E., Kelly, J. T., & Smith, A. C. (2023). A multi-stakeholder approach is needed to reduce the digital divide and encourage equitable access to telehealth. Journal of Telemedicine and Telecare, 29(1), 73–78.35733379
306 Turcios, Y (2023, March 22). Digital access: A super determinant of health. https://www.samhsa.gov/blog/digital-access-super-determinant-health.
307 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings: A literature review.
308 Cos, T. A., LaPollo, A. B., Aussendorf, M., Williams, J. M., Malayter, K., & Festinger, D. S. (2020). Do peer recovery specialists improve outcomes for individuals with substance use disorder in an integrative primary care setting? A program evaluation. Journal of Clinical Psychology in Medical Settings, 27(4), 704–715.31520183
309 Stanojlović, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
310 National Council for Mental Wellbeing. (2022). Establishing peer support services for overdose response: A toolkit for health departments..
311 Eddie, D., Hoffman, L., Vilsaint, C., Abry, A., Bergman, B., Hoeppner, B., … Kelly, J. F. (2019). Lived experience in new models of care for substance use disorder: A systematic review of peer recovery support services and recovery coaching. Frontiers in Psychology, 10, 1052.31263434
312 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258-S266.
313 Stack, E., Hildebran, C., Leichtling, G., Waddell, E. N., Leahy, J. M., Martin, E., & Korthuis, P. T. (2022). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings; A narrative review. Journal of Addiction Medicine, 16(1), 93–100.33560695
314 Government Accountability Office. (2020). Substance use disorder: Medicaid coverage of peer support services for adults (GAO-20-616).
315 National Council for Mental Wellbeing. (2022). Establishing peer support services for overdose response: A toolkit for health departments..
316 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
317 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
318 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings: A literature review..
319 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
320 Gagne, C., Olivet, J., & Davis, L. (2012). Equipping behavioral health systems & authorities to promote peer specialist/peer recovery coaching services: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
321 Bureau of Justice Assistance. (2022). Peer recovery support services in correctional settings. U.S. Department of Justice, Office of Justice Programs.
322 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings: A literature review..
323 NORC at the University of Chicago & Center for Health & Justice at TASC. (2021). Report of the Nation Survey to Assess First Responder Deflection Programs in Response to the Opioid Crisis: Final report. U.S. Department of Justice, Office of Justice Programs, Bureau of Justice Assistance.
324 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6 Suppl. 3), S258-S266.
325 Peer Recovery Center of Excellence. (2021). Peer recovery support: Evolving roles and settings: A literature review..
326 Almeida, M., Day, A., Smith, B., Bianco, C., & Fortuna, K. (2020). Actionable items to address challenges incorporating peer support specialists within an integrated mental health and substance use disorder system: Co-designed qualitative study. Journal of Participatory Medicine, 12(4), e17053.33242015
327 Kelly, J. F., Greene, M. C., & Bergman, B. G. (2018). Beyond abstinence: Changes in indices of quality of life with time in recovery in a nationally representative sample of U.S. adults. Alcoholism, Clinical and Experimental Research, 42(4), 770–780.29473966
328 Paquette, C. E., Daughters, S. B., & Witkiewitz, K. (2022). Expanding the continuum of substance use disorder treatment: Nonabstinence approaches. Clinical Psychology Review, 91, 102110.34864497
329 Paquette, C. E., Daughters, S. B., & Witkiewitz, K. (2022). Expanding the continuum of substance use disorder treatment: Nonabstinence approaches. Clinical Psychology Review, 91, 102110.34864497
330 Paquette, C. E., Daughters, S. B., & Witkiewitz, K. (2022). Expanding the continuum of substance use disorder treatment: Nonabstinence approaches. Clinical Psychology Review, 91, 102110.34864497
331 Hay, K. R., Huhn, A. S., Tompkins, D. A., & Dunn, K. E. (2019). Recovery goals and long-term treatment preference in persons who engage in nonmedical opioid use. Journal of Addiction Medicine, 13(4), 300–305.30633045
332 Kaskutas, L. A., Borkman, T. J., Laudet, A., Ritter, L. A., Witbrodt, J., Subbaraman, M. S., … Bond, J. (2014). Elements that define recovery: The experiential perspective. Journal of Studies on Alcohol and Drugs, 75(6), 999–1010.25343658
333 Witbrodt, J., Kaskutas, L. A., & Grella, C. E. (2015). How do recovery definitions distinguish recovering individuals? Five typologies. Drug and Alcohol Dependence, 148, 109–117.25630961
334 Roos, C. R., Nich, C., Mun, C. J., Babuscio, T. A., Mendonca, J., Miguel, A., … Kiluk, B. D. (2019). Clinical validation of reduction in cocaine frequency level as an endpoint in clinical trials for cocaine use disorder. Drug and Alcohol Dependence, 205, 107648.31677490
335 Bischof, G., Lange, N., Rumpf, H. J., & Preuss, U. W. (2021). Reduced drinking and harm reduction in the treatment of alcohol use disorders. Drugs and Alcohol Today, 21(1), 31–44.
336 Paquette, C. E., Daughters, S. B., & Witkiewitz, K. (2022). Expanding the continuum of substance use disorder treatment: Nonabstinence approaches. Clinical Psychology Review, 91, 102110.34864497
337 Rosenberg, H., Grant, J., & Davis, A. K. (2020). Acceptance of non-abstinence as an outcome goal for individuals diagnosed with substance use disorders: A narrative review of published research. Journal of Studies on Alcohol and Drugs, 81(4), 405–415.32800076
338 Hay, K. R., Huhn, A. S., Tompkins, D. A., & Dunn, K. E. (2019). Recovery goals and long-term treatment preference in persons who engage in nonmedical opioid use. Journal of Addiction Medicine, 13(4), 300–305.30633045
339 Eddie, D., Bergman, B. G., Hoffman, L. A., & Kelly, J. F. (2022). Abstinence versus moderation recovery pathways following resolution of a substance use problem: Prevalence, predictors, and relationship to psychosocial well-being in a U.S. national sample. Alcoholism, Clinical and Experimental Research, 46(2), 312–325.34931320
340 Kelly, J. F., Bergman, B., Hoeppner, B. B., Vilsaint, C., & White, W. L. (2017). Prevalence and pathways of recovery from drug and alcohol problems in the United States population: Implications for practice, research, and policy. Drug and Alcohol Dependence, 181, 162–169.29055821
341 Eddie, D., Bergman, B. G., Hoffman, L. A., & Kelly, J. F. (2022). Abstinence versus moderation recovery pathways following resolution of a substance use problem: Prevalence, predictors, and relationship to psychosocial well-being in a U.S. national sample. Alcoholism, Clinical and Experimental Research, 46(2), 312–325.34931320
342 Eddie, D., Bergman, B. G., Hoffman, L. A., & Kelly, J. F. (2022). Abstinence versus moderation recovery pathways following resolution of a substance use problem: Prevalence, predictors, and relationship to psychosocial well-being in a U.S. national sample. Alcoholism, Clinical and Experimental Research, 46(2), 312–325.34931320
343 Paquette, C. E., Daughters, S. B., & Witkiewitz, K. (2022). Expanding the continuum of substance use disorder treatment: Nonabstinence approaches. Clinical Psychology Review, 91, 102110.34864497
344 Davis, A. K., & Rosenberg, H. (2013). Acceptance of non-abstinence goals by addiction professionals in the United States. Psychology of Addictive Behaviors, 27(4), 1102–1109.23088408
345 Rosenberg, H., Grant, J., & Davis, A. K. (2020). Acceptance of non-abstinence as an outcome goal for individuals diagnosed with substance use disorders: A narrative review of published research. Journal of Studies on Alcohol and Drugs, 81(4), 405–415.32800076
346 Gumbley, S. (2016). Recovery in the 21st century: From shame to strength. Journal of Addictions Nursing, 27(2), 143–147.27272998
347 Abt Associates & Hart Research Associates. (2010). Pathways to healing and recovery: Perspectives from individuals with histories of alcohol and other drug problems. Substance Abuse and Mental Health Services Administration.
348 Kelly, J. F., Bergman, B., Hoeppner, B. B., Vilsaint, C., & White, W. L. (2017). Prevalence and pathways of recovery from drug and alcohol problems in the United States population: Implications for practice, research, and policy. Drug and Alcohol Dependence, 181, 162–169.29055821
349 Recovery Research Institute. (n.d.). Recovery 101. https://www.recoveryanswers.org/recovery-101/pathways-to-recovery/.
350 Substance Abuse and Mental Health Services Administration. (2022, September 13). Recovery and recovery support. https://www.samhsa.gov/fínd-help/recovery#recovery-support.
351 Recovery Research Institute. (n.d.). Faith-based recovery support. https://www.recoveryanswers.org/resource/faith-based-recovery-support/.
352 Davidson, L., Rowe, M., DiLeo, P., Bellamy, C., & Delphin-Rittmon, M. (2021). Recovery-oriented systems of care: A perspective on the past, present, and future. Alcohol Research: Current Reviews, 41(1), 09.
353 Substance Abuse and Mental Health Services Administration. (2020). Treating substance use disorder in older adults. Treatment Improvement Protocol (TIP) Series 26. SAMHSA Publication No. PEP20-02-01-011. Substance Abuse and Mental Health Services Administration.
354 Recovery Research Institute. (n.d.). Faith-based recovery support. https://www.recoveryanswers.org/resource/faith-based-recovery-support/.
355 Hidalgo, B. E., Derose, K. P., Kanouse, D. E., Mendel, P. J., Bluthenthal, R. N., & Oden, C. W. (2019). Urban religious congregations' responses to community substance use: An exploratory study of four cases. Journal of Religion and Health, 58(4), 1340–1355.30835054
356 White, W. L. (2007). Addiction recovery: Its definition and conceptual boundaries. Journal of Substance Abuse Treatment, 33, 229–241.17889295
357 Best, D., Vanderplasschen, W., Van de Mheen, D., De Maeyer, J., Colman, C., Vander Laenen, F., … Nagelhout, G. E. (2018). REC-PATH (recovery pathways): Overview of a four-country study of pathways to recovery from problematic drug use. Alcoholism Treatment Quarterly, 36(4), 517–529.
358 American Psychiatric Association. (2022). Diagnostic and statistical manual of mental disorders (5th ed., text rev.).
359 McLellan, A. T (2017). Substance misuse and substance use disorders: Why do they matter in healthcare? Transactions of the American Clinical and Climatological Association, 128, 112–130.28790493
360 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
361 McCabe, S. E., West, B. T., Strobbe, S., & Boyd, C. J. (2018). Persistence/recurrence of and remission from DSM-5 substance use disorders in the United States: Substance-specific and substance-aggregated correlates. Journal of Substance Abuse Treatment, 93, 38–48.30126540
362 Larimer, M. E., Palmer, R. S., & Marlatt, G. A. (1999). Relapse prevention: An overview of Marlatt's cognitive-behavioral model. Alcohol Research and Health, 23(2), 151–160.10890810
363 Marlatt, G. A., Parks, G. A., & Witkiewitz, K. (2002). Clinical guidelines for implementing relapse prevention therapy: A guideline developed for behavioral health recovery management project. University of Washington.
364 Marlatt, G. A., & Witkiewitz, K. (2005). Relapse prevention for alcohol and drug problems. In G. A. Marlatt & D. M. Donovan (Eds.), Relapse prevention: Maintenance strategies in the treatment of addictive behaviors (2nd ed., pp. 1–44). Guilford Press.
365 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
366 Ward, A., Freedland, T., Rohovit, J., & MeyerKalos, P. (2016). Relapse prevention training (Clinical Tip No. 6). Center for Practice Transformation, University of Minnesota.
367 Hsu, S. H., & Marlatt, G. A. (2011). Relapse prevention in substance use. In D. B. Cooper (Ed.), Practice in mental health-substance use (pp. 203–217). CRC Press.
368 Melemis, S. M. (2015). Relapse prevention and the five rules of recovery. Yale Journal of Biology and Medicine, 88(3), 325–332.26339217
369 Melemis, S. M. (2015). Relapse prevention and the five rules of recovery. Yale Journal of Biology and Medicine, 88(3), 325–332.26339217
370 Restrepo-Guzman, R., Li, D., & Lynn, G. (2020). Recovery from addiction: Maintenance and preventing relapse. In C. Marienfeld (Ed.), Absolute Addiction Psychiatry Review (pp. 87–101). Springer Nature.
371 Melemis, S. M. (2015). Relapse prevention and the five rules of recovery. Yale Journal of Biology and Medicine, 88(3), 325–332.26339217
372 Restrepo-Guzman, R., Li, D., & Lynn, G. (2020). Recovery from addiction: Maintenance and preventing relapse. In C. Marienfeld (Ed.), Absolute Addiction Psychiatry Review (pp. 87–101). Springer Nature.
373 Melemis, S. M. (2015). Relapse prevention and the five rules of recovery. Yale Journal of Biology and Medicine, 88(3), 325–332.26339217
374 U.S. Department of Veterans Affairs. (2022). Reducing relapse risk. https://www.va.gov/WHOLEHEALTHLIBRARY/tools/reducing-relapse-risk.asp.
375 U.S. Department of Veterans Affairs. (2022). Reducing relapse risk. https://www.va.gov/WHOLEHEALTHLIBRARY/tools/reducing-relapse-risk.asp.
376 White, W. H. (2020, September 24). Stop kicking people out of addiction treatment (2020 update). Recoveryblog. https://www.chestnut.org/Blog/Posts/363/William-White/2020/9/Stop-Kicking-People-out-of-Addiction-Treatment-2020-Update/blog-post/.
377 Walton, M. T (2018). Administrative discharges in addiction treatment: Bringing practice in line with ethics and evidence. Social Work, 63(1), 85–90.29140509
378 DiClemente, C. C., & Crisafulli, M. A. (2017). Alcohol relapse and change needs a broader view than counting drinks. Alcoholism, Clinical and Experimental Research, 41(2), 266–269.28029170
379 Ignaszewski, M. J. (2021). The epidemiology of drug abuse. Journal of Clinical Pharmacology, 61(Suppl. 2), S10–S17.34396554
380 Uhl, G. R., Koob, G. F., & Cable, J. (2019). The neurobiology of addiction. Annals of the New York Academy of Sciences, 1451(1), 5–28.30644552
381 Ignaszewski, M. J. (2021). The epidemiology of drug abuse. Journal of Clinical Pharmacology, 61(Suppl. 2), S10–S17.34396554
382 Laudet, A. (2018). 2013). “Life in Recovery”: Report on the survey findings (p. 1). Faces and Voices of Recovery.
383 Ignaszewski, M. J. (2021). The epidemiology of drug abuse. Journal of Clinical Pharmacology, 61(Suppl. 2), S10–S17.34396554
384 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
385 Peterson, C., Li, M., Xu, L., Mikosz, C. A., & Luo, F. (2021). Assessment of annual cost of substance use disorder in US hospitals. JAMA Network Open, 4(3), e210242.33666661
386 Centers for Disease Control and Prevention, National Center for Health Statistics. (2021, November 17). Drug overdose deaths in the U.S. top 100,000 annually [Press release]. https://www.cdc.gov/nchs/pressroom/nchspressreleases/2021/20211117.htm.
387 Centers for Disease Control. (2020). Impaired driving: Get the facts. https://www.cdc.gov/transportationsafety/impaireddriving/impaired-drvfactsheet.html.
388 Murphy, S. M. (2020). The cost of opioid use disorder and the value of aversion. Drug and Alcohol Dependence, 217, 108382.33183909
389 National Institute on Drug Abuse. (2021, December). How much does opioid treatment cost? Medications to Treat Opioid Use Disorder Research Report. https://nida.nih.gov/publications/research-reports/medications-to-treat-opioid-addiction/how-much-does-opioid-treatment-cost.
390 The Pew Charitable Trusts. (2018) (2021). Local spending on jails tops $25 billion in latest nationwide data [Issue brief].
391 United States Courts. (2017, August 17). Incarceration costs significantly more than supervision. https://www.uscourts.gov/news/2017/08/17/incarceration-costs-significantly-more-supervision.
392 NORC at the University of Chicago. (2020, December 2). New analysis: Employers stand to save an average of $8,500 for supporting each employee in recovery from a substance use disorder [Press release]. https://www.norc.org/NewsEventsPublications/PressReleases/Pages/new-analysis-employers-stand-to-save-an-average-of-8500-for-supporting-each-employee-in-recovery-from-a-substance-use-dis.aspx.
393 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol drugs, and health. U.S. Department of Health and Human Services.
394 Ignaszewski, M. J. (2021). The epidemiology of drug abuse. Journal of Clinical Pharmacology, 61(Suppl. 2), S10–S17.34396554
395 Substance Abuse and Mental Health Services Administration. (2010). Recovery-oriented systems of care (ROSC) resource guide. Substance Abuse and Mental Health Services Administration.
396 DiClemente, C. C., Norwood, A. E., Gregory, W. H., Travaglini, L., Graydon, M. M., & Corno, C. M. (2016). Consumer-centered, collaborative, and comprehensive care: The core essentials of recovery-oriented system of care. Journal of Addictions Nursing, 27(2), 94–100.27272993
397 DiClemente, C. C., Norwood, A. E., Gregory, W. H., Travaglini, L., Graydon, M. M., & Corno, C. M. (2016). Consumer-centered, collaborative, and comprehensive care: The core essentials of recovery-oriented system of care. Journal of Addictions Nursing, 27(2), 94–100.27272993
398 Substance Abuse and Mental Health Services Administration. (2012). Operationalizing recovery-oriented systems: Expert panel meeting report. Substance Abuse and Mental Health Services Administration.
399 Best, D., & Colman, C. (2019). Let's celebrate recovery. Inclusive cities working together to support social cohesion. Addiction Research and Theory, 271, 55–64.
400 Davidson, L., Rowe, M., DiLeo, P., Bellamy, C., & Delphin-Rittmon, M. (2021). Recovery-oriented systems of care: A perspective on the past, present, and future. Alcohol Research: Current Reviews, 41(1), 09.34377618
401 Davidson, L., Rowe, M., DiLeo, P., Bellamy, C., & Delphin-Rittmon, M. (2021). Recovery-oriented systems of care: A perspective on the past, present, and future. Alcohol Research: Current Reviews, 41(1), 09.34377618
402 Illinois Department of Human Services. (n.d.). Illinois recovery oriented system of care (ROSC) councils. https://www.dhs.state.il.us/page.aspx?item=117096.
403 New York State Office of Addiction Services and Supports. (n.d.). Recovery-oriented systems of care: The foundation for recovery in New York state. https://oasas.ny.gov/providers/recovery-oriented-systems-care.
404 Bitting, S., Nash, A., & Ochoa, A. (2016). Houston recovery initiative: A rich case study of building recovery communities one voice at a time. Journal of Addictions Nursing, 27(2), 120–126.27272996
405 Ohio Association of County Behavioral Health Authorities. (n.d.). Recovery-oriented systems of care. https://www.oacbha.org/recovery-orientedsystemsofc.php.
406 Fitzgerald, M. (2019, February 4). Scott County, IN: Where it's cool to be in recovery [Blog post]. https://niatx.attcnetwork.org/2019/01/scott-county-in-where-its-cool-to-be-in.html.
407 National Academies of Sciences, Engineering, and Medicine. (2016). Measuring recovery from substance use or mental disorders: Workshop summary. National Academies Press.
408 Brown, A. M., & Ashford, R. D. (2019). Recovery-informed theory: Situating the subjective in the science of substance use disorder recovery. Journal of Recovery Science, 1(3), 1–15.
409 McDaniel, J. M., Brown, A. M., Thompson Heller, A., Johnston, T. W., Bergman, B., Bohler, R., … Ashford, R. D. (2020). Interdisciplinary expansions: Applying recovery-informed theory to interdisciplinary areas of recovery science research. Alcoholism Treatment Quarterly, 38(4), 457–469.
410 Brown, A. M., & Ashford, R. D. (2019). Recovery-informed theory: Situating the subjective in the science of substance use disorder recovery. Journal of Recovery Science, 1(3), 1–5.
411 Humphreys, K., & Bickel, W. K. (2018). Toward a neuroscience of long-term recovery from addiction (p. 875). JAMA Psychiatry, 75(9), 875–876.29847627
412 Humphreys, K., & Bickel, W. K. (2018). Toward a neuroscience of long-term recovery from addiction (p. 875). JAMA Psychiatry, 75(9), 875–876.29847627
413 Daviet, R., Aydogan, G., Jagannathan, K., Spilka, N., Koellinger, P. D., Kranzler, H. R., … Wetherill, R. R. (2022). Associations between alcohol consumption and gray and white matter volumes in the UK Biobank. Nature Communications, 13(1), 1175.
414 Hampton, W. H., Hanik, I. M., & Olson, I. R. (2019). Substance abuse and white matter: Findings, limitations, and future of diffusion tensor imaging research. Drug and Alcohol Dependence, 197, 288–298.30875650
415 Nie, L., Ghahremani, D. G., Mandelkern, M. A., Dean, A. C., Luo, W., Ren, A., … London, E. D. (2021). The relationship between duration of abstinence and gray-matter brain structure in chronic methamphetamine users. American Journal of Drug and Alcohol Abuse, 47(1), 65–73.33426968
416 Korponay, C., Kosson, D. S., Decety, J., Kiehl, K. A., & Koenigs, M. (2017). Brain volume correlates with duration of abstinence from substance abuse in a region-specific and substance-specific manner. Biological Psychiatry. Cognitive Neuroscience and Neuroimaging, 2(7), 626–635.29308437
417 Meyerhoff, D. J., & Durazzo, T. C. (2020). Not all is lost for relapsers: Relapsers with low WHO risk drinking levels and complete abstainers have comparable regional gray matter volumes. Alcoholism: Clinical and Experimental Research, 44(7), 1479–1487.
418 Martz, M. E., Hart, T., Heitzeg, M. M., & Peltier, S. J. (2020). Neuromodulation of brain activation associated with addiction: A review of real-time fMRI neurofeedback studies. NeuroImage. Clinical, 27, 102350.32736324
419 Coles, A. S., Kozak, K., & George, T. P. (2018). A review of brain stimulation methods to treat substance use disorders. American Journal on Addictions, 27(2), 71–91.29457674
420 Luigjes, J., Segrave, R., de Joode, N., Figee, M., & Denys, D. (2019). Efficacy of invasive and non-invasive brain modulation interventions for addiction. Neuropsychology Review, 29(1), 116–138.30536145
421 Ekhtiari, H., Tavakoli, H., Addolorato, G., Baeken, C., Bonci, A., Campanella, S., … Hanlon, C.A. (2019). Transcranial electrical and magnetic stimulation (tES and TMS) for addiction medicine: A consensus paper on the present state of the science and the road ahead. Neuroscience and Biobehavioral Reviews, 104, 118–140.31271802
422 Torres-Castaño, A., Rivero-Santana, A., Perestelo-Pérez, L., Duarte-Díaz, A., Toledo-Chavarri, A., Ramos-Garcia, V., … Serrano-Perez, P. (2021). Transcranial magnetic stimulation for the treatment of cocaine addiction: A systematic review. Journal of Clinical Medicine, 10(23), 5595.34884297
423 Coles, A. S., Kozak, K., & George, T. P. (2018). A review of brain stimulation methods to treat substance use disorders. American Journal on Addictions, 27(2), 71–91.
424 Coles, A. S., Kozak, K., & George, T. P. (2018). A review of brain stimulation methods to treat substance use disorders. American Journal on Addictions, 27(2), 71–91.29457674
425 Coles, A. S., Kozak, K., & George, T. P. (2018). A review of brain stimulation methods to treat substance use disorders. American Journal on Addictions, 27(2), 71–91.29457674
426 Eddie, D., Bergman, B. G., Hoffman, L. A., & Kelly, J. F. (2022). Abstinence versus moderation recovery pathways following resolution of a substance use problem: Prevalence, predictors, and relationship to psychosocial well-being in a U.S. national sample. Alcoholism, Clinical and Experimental Research, 46(2), 312–325.34931320
427 Witkiewitz, K., Pearson, M. R., Wilson, A. D., Stein, E. R., Votaw, V. R., Hallgren, K. A., Tucker, J. A. (2020). Can alcohol use disorder recovery include some heavy drinking? A replication and extension up to 9 years following treatment. Alcoholism, Clinical and Experimental Research, 44(9), 1862–1874.32761936
428 Pearson, M. R., Wilson, A. D., Richards, D. K., & Witkiewitz, K. (2021). Reconsidering alcohol treatment non-responders: psychosocial functioning among heavy drinkers 3 years following treatment. Addiction (Abingdon, England), 116(5), 1262–1269.33009685
429 Witkiewitz, K., Pearson, M. R., Wilson, A. D., Stein, E. R., Votaw, V. R., Hallgren, K. A., Tucker, J. A. (2020). Can alcohol use disorder recovery include some heavy drinking? A replication and extension up to 9 years following treatment. Alcoholism, Clinical and Experimental Research, 44(9), 1862–1874.32761936
430 Kiluk, B. D., Babuscio, T. A., Nich, C., & Carroll, K. M. (2017). Initial validation of a proxy indicator of functioning as a potential tool for establishing a clinically meaningful cocaine use outcome. Drug and Alcohol Dependence, 179, 400–407.28858744
431 Bickel, W. K., Johnson, M. W., Koffarnus, M. N., MacKillop, J., & Murphy, J. G. (2014). The behavioral economics of substance use disorders: Reinforcement pathologies and their repair. Annual Review of Clinical Psychology, 10, 641–677.
432 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
433 Field, M., Heather, N., Murphy, J. G., Stafford, T., Tucker, J. A., & Witkiewitz, K. (2020). Recovery from addiction: Behavioral economics and value-based decision making. Psychology of Addictive Behaviors, 34(1), 182–193.31599604
434 White, W. (2013, July 13). Recovery durability: The 5-year set point [Blog post]. https://www.chestnut.org/Blog/Posts/24/William-White/2013/7/Recovery-Durability-The-5Year-Set-Point/blog-post/blog-and-news-postings-details/.
435 Kelly, J. F., Greene, M. C., & Bergman, B. G. (2018). Beyond abstinence: Changes in indices of quality of life with time in recovery in a nationally representative sample of US adults. Alcoholism: Clinical and Experimental Research, 42(4), 770–780.29473966
436 Schmidt, S., Mühlan, H., & Power, M. (2006). The EUROHIS-QOL 8-item index: Psychometric results of a cross-cultural field study. The European Journal of Public Health, 16(4), 420–428.16141303
437 American Psychiatric Association. (2022). Diagnostic and statistical manual of mental disorders (5th ed., text rev.).
438 National Association of Recovery Residences. (n.d.). Recovery residence levels of support and standards criteria matrix. https://narronline.org/wp-content/uploads/2016/12/NARR_levels_summary.pdf.
439 National Council for Mental Well-Being. (2021). Demonstrating the value of recovery housing: Technical expert panel findings..
440 Mericle, A. A., Slaymaker, V., Gliske, K., Ngo, Q., & Subbaraman, M. S. (2022). The role of recovery housing during outpatient substance use treatment. Journal of Substance Abuse Treatment, 133, 108638.34657785
441 Mericle, A. A., Polcin, D. L., Hemberg, J., & Miles, J. (2017). Recovery housing: Evolving models to address resident needs. Journal of Psychoactive Drugs, 49(4), 352–361.28657823
442 Recovery Research Institute. (n.d.). For people in treatment, who engages with recovery residences, and does it boost retention? https://www.recoveryanswers.org/research-post/deeper-dive-recovery-residence-participants-who-more-likely-use-them-how-affect-engagement-outpatient-care/.
443 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
444 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
445 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
446 Recovery Research Institute. (n.d.). Recovery community centers: Is participation in these newer recovery support services associated with better functioning and quality of life? https://www.recoveryanswers.org/research-post/recovery-community-centers-associated-with-well-being/.
447 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
448 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions (p. S263). American Journal of Preventive Medicine, 54(6 Suppl. 3), S258-S266.
449 Chapman, S., Blash, L. K., Mayer, K., & Spetz, J. (2018). Emerging roles for peer providers in mental and substance use disorders. American Journal of Preventive Medicine, 54(6 Suppl. 3), S267-S274.
450 Substance Abuse and Mental Health Services Administration. (2021). The substance use disorder counseling competency framework: An overview. Advisory. SAMHSA Publication No. PEP20-02-01-017. Substance Abuse and Mental Health Services Administration.
451 Raiker, N., Aouthmany, M., & Ezra, N. (2016). Dermatologic signs and symptoms of substance abuse. Journal of Clinical & Experimental Dermatology Research, 7(2), 1000337.
452 Metzl, J. M., & Hansen, H. (2014). Structural competency: Theorizing a new medical engagement with stigma and inequality. Social Science & Medicine (1982), 103, 126–133.24507917
453 Ali, A., & Sichel, C. E. (2014). Structural competency as a framework for training in counseling psychology. Counseling Psychologist, 42(7), 901–918.
454 Sukhera, J., Knaak, S., Ungar, T., & Rehman, M. (2022). Dismantling structural stigma related to mental health and substance use: An educational framework. Academic Medicine, 97(2), 175–181.34647920
455 Sukhera, J., Knaak, S., Ungar, T., & Rehman, M. (2022). Dismantling structural stigma related to mental health and substance use: An educational framework. Academic Medicine, 97(2), 175–181.34647920
456 O'Gurek, D. T., & Henke, C. (2018). A practical approach to screening for social determinants of health. Family Practice Management, 25(3), 7–12.29989777
457 Moen, M., Storr, C., German, D., Friedmann, E., & Johantgen, M. (2020). A review of tools to screen for social determinants of health in the United States: A practice brief. Population Health Management, 23(6), 422–429.31910355
458 Moen, M., Storr, C., German, D., Friedmann, E., & Johantgen, M. (2020). A review of tools to screen for social determinants of health in the United States: A practice brief. Population Health Management, 23(6), 422–429.31910355
459 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
460 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
461 Marsh, J. C., Amaro, H., Kong, Y., Khachikian, T., & Guerrero, E. (2021). Gender disparities in access and retention in outpatient methadone treatment for opioid use disorder in low-income urban communities. Journal of Substance Abuse Treatment, 127, 108399.34134873
462 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
463 Substance Abuse and Mental Health Services Administration. (2014). Improving cultural competence. Treatment Improvement Protocol (TIP) Series 59. HHS Publication No. (SMA) 14-4849. Substance Abuse and Mental Health Services Administration.
464 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
465 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
466 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005, NSDUH Series H-57. Substance Abuse and Mental Health Services Administration, Center for Behavioral Health Statistics and Quality.
467 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
468 Gameon, J. A., & Skewes, M. C. (2021). Historical trauma and substance use among American Indian people with current substance use problems. Psychology of Addictive Behaviors, 35(3), 295–309.33829816
469 Mennis, J., & Stapler, G. J. (2016). Racial and ethnic disparities in outpatient substance use disorder treatment episode completion for different substances. Journal of Substance Abuse Treatment, 63, 25–33.26818489
470 Martin, C. E., Parlier-Ahmad, A. B., Beck, L., Scialli, A., & Terplan, M. (2022). Need for and receipt of substance use disorder treatment among adults, by gender, in the United States. Public Health Reports (Washington, D.C.: 1974), 137(5), 955–963.34546835
471 Matsuzaka, S., & Knapp, M. (2020). Anti-racism and substance use treatment: Addiction does not discriminate, but do we? Journal of Ethnicity in Substance Abuse, 19(4), 567–593.30642230
472 Hall, O. T., Jordan, A., Teater, J., Dixon-Shambley, K., McKiever, M. E., Baek, M., … Fielin, D. A. (2022). Experiences of racial discrimination in the medical setting and associations with medical mistrust and expectations of care among black patients seeking addiction treatment. Journal of Substance Abuse Treatment, 133, 108551.34244014
473 Hall, O. T., Jordan, A., Teater, J., Dixon-Shambley, K., McKiever, M. E., Baek, M., … Fielin, D. A. (2022). Experiences of racial discrimination in the medical setting and associations with medical mistrust and expectations of care among black patients seeking addiction treatment. Journal of Substance Abuse Treatment, 133, 108551.34244014
474 Pinedo, M., Zemore, S., & Rogers, S. (2018). Understanding barriers to specialty substance abuse treatment among Latinos. Journal of Substance Abuse Treatment, 94, 1–8.30243409
475 American Psychological Association. (2016). Stress in America™: The impact of discrimination. Stress in America™ Survey. https://www.apa.org/news/press/releases/stress/.
476 Substance Abuse and Mental Health Services Administration. (2020). The opioid crisis and the Black/African American population: An urgent issue. Publication No. PEP20-05-02-001. Substance Abuse and Mental Health Services Administration, Office of Behavioral Health Equity.
477 Lagisetty, P. A., Ross, R., Bohnert, A., Clay, M., & Maust, D. T. (2019). Buprenorphine treatment divide by race/ethnicity and payment. JAMA Psychiatry, 76(9), 979–981.31066881
478 Goedel, W. C., Shapiro, A., Cerdá, M., Tsai, J. W., Hadland, S. E., & Marshall, B. (2020). Association of racial/ethnic segregation with treatment capacity for opioid use disorder in counties in the United States. JAMA Network Open, 3(4), e203711.32320038
479 Kleinman, R. A. (2020). Comparison of driving times to opioid treatment programs and pharmacies in the US. JAMA Psychiatry, 77(11), 1163–1171.32667648
480 Marsh, J. C., Amaro, H., Kong, Y., Khachikian, T., & Guerrero, E. (2021). Gender disparities in access and retention in outpatient methadone treatment for opioid use disorder in low-income urban communities. Journal of Substance Abuse Treatment, 127, 108399.34134873
481 Redmond, M. L., Smith, S., & Collins, T. C. (2020). Exploring African-American women's experiences with substance use treatment: A review of the literature. Journal of Community Psychology, 48(2), 337–350.31609461
482 Martin, C. E., Parlier-Ahmad, A. B., Beck, L., Scialli, A., & Terplan, M. (2022). Need for and receipt of substance use disorder treatment among adults, by gender, in the United States. Public Health Reports (Washington, D.C.: 1974), 137(5), 955–963.34546835
483 Martin, C. E., Parlier-Ahmad, A. B., Beck, L., Scialli, A., & Terplan, M. (2022). Need for and receipt of substance use disorder treatment among adults, by gender, in the United States. Public Health Reports (Washington, D.C.: 1974), 137(5), 955–963.34546835
484 Martin, C. E., Parlier-Ahmad, A. B., Beck, L., Scialli, A., & Terplan, M. (2022). Need for and receipt of substance use disorder treatment among adults, by gender, in the United States. Public Health Reports (Washington, D.C.: 1974), 137(5), 955–963.34546835
485 Batchelder, A. W., Stanton, A. M., Kirakosian, N., King, D., Grasso, C., Potter, J., … O'Cleirigh, C. (2021). Mental health and substance use diagnoses and treatment disparities by sexual orientation and gender in a community health center sample. LGBTHealth, 8(4), 290–299.
486 Williams, N. D., & Fish, J. N. (2020). The availability of LGBT-specific mental health and substance abuse treatment in the United States. Health Services Research, 55(6), 932–943.32970327
487 Williams, N. D., & Fish, J. N. (2020). The availability of LGBT-specific mental health and substance abuse treatment in the United States. Health Services Research, 55(6), 932–943.32970327
488 Williams, N. D., & Fish, J. N. (2020). The availability of LGBT-specific mental health and substance abuse treatment in the United States. Health Services Research, 55(6), 932–943.32970327
489 Matsuzaka, S. (2018). Transgressing gender norms in addiction treatment: Transgender rights to access within gender-segregated facilities. Journal of Ethnicity in Substance Abuse, 17(4), 420–433.28632095
490 Williams, N. D., & Fish, J. N. (2020). The availability of LGBT-specific mental health and substance abuse treatment in the United States. Health Services Research, 55(6), 932–943.32970327
491 Amiri, S., McDonell, M. G., Denney, J. T., Buchwald, D., & Amram, O. (2021). Disparities in access to opioid treatment programs and office-based buprenorphine treatment across the rural-urban and area deprivation continua: A US nationwide small area analysis. Value in Health, 24(2), 188–195.33518025
492 Lister, J. J., Weaver, A., Ellis, J. D., Himle, J. A., & Ledgerwood, D. M. (2020). A systematic review of rural-specific barriers to medication treatment for opioid use disorder in the United States. American Journal of Drug and Alcohol Abuse, 46(3), 273–288.31809217
493 Lister, J. J., Weaver, A., Ellis, J. D., Himle, J. A., & Ledgerwood, D. M. (2020). A systematic review of rural-specific barriers to medication treatment for opioid use disorder in the United States. American Journal of Drug and Alcohol Abuse, 46(3), 273–288.31809217
494 U.S. Drug Enforcement Administration. (2021, June 28). DEA finalizes measures to expand medication-assisted treatment. https://www.dea.gov/press-releases/2021/06/28/dea-finalizes-measures-expand-medication-assisted-treatment.
495 Rural Health Information Hub. (n.d.). Barriers to preventing and treating substance use disorders in rural communities. Retrieved November 22, 2022, from https://www.ruralhealthinfo.org/toolkits/substance-abuse/1/barriers.
496 Clary, E., Ribar, C., Weigensberg, E., Radel, L., & Madden, E. (2020). Challenges in providing substance use disorder treatment to child welfare clients in rural communities. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
497 Substance Abuse and Mental Health Services Administration. (2016). Rural behavioral health: Telehealth challenges and opportunities. In Brief, 9(2).
498 Federal Communications Commission. (2021, January 19). FCC annual broadband report shows digital divide is rapidly closing. In Inquiry concerning deployment of advanced telecommunications capability to all Americans in a reasonable and timely fashion. GN Docket No. 20-269. https://www.fcc.gov/document/fcc-annual-broadband-report-shows-digital-divide-rapidly-closing.
499 Lewis, B., Hoffman, L., Garcia, C. C., & Nixon, S. J. (2018). Race and socioeconomic status in substance use progression and treatment entry. Journal of Ethnicity in Substance Abuse, 17(2), 150–166.28846065
500 Baptiste-Roberts, K., & Hossain, M. (2018). Socioeconomic disparities and self-reported substance abuse-related problems. Addiction & Health, 10(2), 112–122.31069035
501 Priester, M. A., Browne, T., Iachini, A., Clone, S., DeHart, D., & Seay, K. D. (2016). Treatment access barriers and disparities among individuals with co-occurring mental health and substance use disorders: An integrative literature review. Journal of Substance Abuse Treatment, 61, 47–59.26531892
502 Novotna, G., Johner, R., McCarron, M., Novik, N., Jeffery, B., Taylor, M., & Jones, M. (2017). Assessment and treatment for persons with coexisting ability and substance use issues: A review and analysis of the literature. Journal of Social Work in Disability & Rehabilitation, 16(2), 141–160.28281941
503 Czeisler, M. E., Board, A., Thierry, J. M., Czeisler, C. A., Rajaratnam, S. M. W., Howard, M. E., & Clarke, K. E. N. (2021). Mental health and substance use among adults with disabilities during the COVID-19 pandemic—United States, February-March 2021. Morbidity and Mortality Weekly Report, 70(34), 1142–1149.34437518
504 Czeisler, M. E., Board, A., Thierry, J. M., Czeisler, C. A., Rajaratnam, S. M. W., Howard, M. E., & Clarke, K. E. N. (2021). Mental health and substance use among adults with disabilities during the COVID-19 pandemic—United States, February-March 2021. Morbidity and Mortality Weekly Report, 70(34), 1142–1149.34437518
505 Ledingham, E., Adams, R. S., Heaphy, D., Duarte, A., & Reif, S. (2022). Perspectives of adults with disabilities and opioid misuse: Qualitative findings illuminating experiences with stigma and substance use treatment. Disability and Health Journal, 101292.
506 Novotna, G., Johner, R., McCarron, M., Novik, N., Jeffery, B., Taylor, M., & Jones, M. (2017). Assessment and treatment for persons with coexisting ability and substance use issues: A review and analysis of the literature. Journal of Social Work in Disability & Rehabilitation, 16(2), 141–160.28281941
507 Ledingham, E., Adams, R. S., Heaphy, D., Duarte, A., & Reif, S. (2022). Perspectives of adults with disabilities and opioid misuse: Qualitative findings illuminating experiences with stigma and substance use treatment. Disability and Health Journal, 101292.
508 Austin, E. J., Tsui, J. I., Barry, M. P., Tung, E., Glick, S. N., Ninburg, M., & Williams, E. C. (2022). Health care-seeking experiences for people who inject drugs with hepatitis C: Qualitative explorations of stigma. Journal of Substance Abuse Treatment, 137, 108684.34911656
509 Claborn, K., Hill, R., & Kioumarsi, A. (2021). Improving linkage and retention in treatment among people living with HIV and comorbid substance use. AIDS Care, 1–6. Advance online publication.
510 Austin, E. J., Tsui, J. I., Barry, M. P., Tung, E., Glick, S. N., Ninburg, M., & Williams, E. C. (2022). Health care-seeking experiences for people who inject drugs with hepatitis C: Qualitative explorations of stigma. Journal of Substance Abuse Treatment, 137, 108684.34911656
511 U.S. Department of Health and Human Services. (n.d.). Pain management best practices interagency task force: Stigma Factsheet. https://www.hhs.gov/sites/default/files/pmtf-fact-sheet-stigma508-2019-08-13.pdf.
512 Claborn, K., Hill, R., & Kioumarsi, A. (2021). Improving linkage and retention in treatment among people living with HIV and comorbid substance use. AIDS Care, 1–6. Advance online publication.
513 Stenersen, M. R., Thomas, K., Struble, C., Moore, K. E., Burke, C., & McKee, S. (2022). The impact of self-help groups on successful substance use treatment completion for opioid use: An intersectional analysis of race/ethnicity and sex. Journal of Substance Abuse Treatment, 136, 108662.34840040
514 English, D., Rendina, H. J., & Parsons, J. T. (2018). The effects of intersecting stigma: A longitudinal examination of minority stress, mental health, and substance use among Black, Latino, and multiracial gay and bisexual men. Psychology of Violence, 8(6), 669–679.30881729
515 Schuler, M. S., Prince, D. M., Breslau, J., & Collins, R. L. (2020). Substance use disparities at the intersection of sexual identity and race/ethnicity: Results from the 2015-2018 National Survey on Drug Use and Health. LGBT Health, 7(6), 283–291.32543315
516 Marcelin, J. R., Siraj, D. S., Victor, R., Kotadia, S., & Maldonado, Y. A. (2019). The impact of unconscious bias in healthcare: How to recognize and mitigate it. Journal of Infectious Diseases, 220(220 Suppl. 2), S62–S73.31430386
517 Biancarelli, D. L., Biello, K. B., Childs, E., Drainoni, M., Salhaney, P., Edeza, A., … Bazzi, A. R. (2019). Strategies used by people who inject drugs to avoid stigma in healthcare settings. Drug and Alcohol Dependence, 198, 80–86.30884432
518 Amaro, H., Sanchez, M., Bautista, T., & Cox, R. (2021). Social vulnerabilities for substance use: Stressors, socially toxic environments, and discrimination and racism. Neuropharmacology, 188, 108518.33716076
519 Mendiola, C. K., Galetto, G., & Fingerhood, M. (2018). An exploration of emergency physicians' attitudes toward patients with substance use disorder (p. 133). Journal of Addiction Medicine, 12(2), 132–135.29351141
520 Martin, M., Snyder, H. R., Otway, G., Holpit, L., Day, L. W., & Seidman, D. (2022). In-hospital substance use policies: An opportunity to advance equity, reduce stigma, and offer evidence-based addiction care. Journal of Addiction Medicine, 10–1097.
521 Strike, C., Robinson, S., Guta, A., Tan, D. H., O'Leary, B., Cooper, C., … Carusone, S. C. (2020). Illicit drug use while admitted to hospital: Patient and health care provider perspectives. PLoS ONE, 15(3), e0229713.
522 Muncan, B., Walters, S. M., Ezell, J., & Ompad, D. C. (2020). “They look at us like junkies:” Influences of drug use stigma on the healthcare engagement of people who inject drugs in New York City. Harm Reduction Journal, 17(53), online publication.
523 Strike, C., Robinson, S., Guta, A., Tan, D. H., O'Leary, B., Cooper, C., … Carusone, S. C. (2020). Illicit drug use while admitted to hospital: Patient and health care provider perspectives. PLoS ONE, 15(3), e0229713.32134973
524 Eaton, E. F., Westfall, A. O., McClesky, B., Paddock, C. S., Lane, P. S., Cropsey, K. L., & Lee, R. A. (2020, March). In-hospital illicit drug use and patient-directed discharge: Barriers to care for patients with injection-related infections. Open Forum Infectious Diseases, 7(3), ofaa074.32258203
525 Martin, M., Snyder, H. R., Otway, G., Holpit, L., Day, L. W., & Seidman, D. (2022). In-hospital substance use policies: An opportunity to advance equity, reduce stigma, and offer evidence-based addiction care. Journal of Addiction Medicine, 10–1097.
526 Drake, C. D., Trent Codd, R., & Terry, C. (2018). Assessing the validity of implicit and explicit measures of stigma toward clients with substance use disorders among mental health practitioners, Journal of Contextual Behavioral Science, 8, 44–54.
527 Center for the Application of Prevention Technologies. (2017). Words matter: How language choice can reduce stigma. HHS Publication No. 508-2019-08-13. Substance Abuse and Mental Health Services Administration.
528 Rockefeller University. (n.d.). Bystander intervention. Retrieved July 7, 2022, from https://www.rockefeller.edu/education-and-training/bystander-intervention/.
529 Tenney, L. (n.d.). Being an active bystander: Strategies for challenging the emergence of bias. The Ohio State University, Kirwan Institute for the Study of Race & Ethnicity. https://kirwaninstitute.osu.edu/sites/default/flles/2019-08/ActiveBystander_Handout2019.pdf.
530 Young, A., Edwards, J. K., Nikels, H. J., & Standefer, S. R. (2017). Strengths-based counseling 2.0: Continuing the discussion. In J. K. Edwards, A. Young, & H. J. Nikels (Eds.), Handbook of strengths-based clinical practices: Finding common factors. Routledge.
531 Best, D., Edwards, M., Cano, I., Durrance, J., Leyman, J., & White, W. L. (2018, May-June). Strengths planning for building recovery capital. Counselor, 3, 32–37.
532 Goscha, R. J. (2020). Strengths model case management: Moving strengths from concept to action. In A. N. Mendenhall, & M. M. Carney (Eds.), Rooted in strengths: Celebrating strengths perspective in social work (pp. 165–186). University of Kansas, School of Social Welfare.
533 Rapp, C. A., & Goscha, R. J. (2012). The strengths model: A recovery-oriented approach to mental health services (3rd ed.). Oxford University Press.
534 Giacomucci, S. (2021). Social work, sociometry, and psychodrama: Experiential approaches for group therapists, community leaders, and social workers. Springer.
535 Giacomucci, S. (2021). Social work, sociometry, and psychodrama: Experiential approaches for group therapists, community leaders, and social workers. Springer.
536 Magyar-Moe, J. L., Owens, R. L., & Conoley, C. W. (2015). Positive psychological interventions in counseling: What every counseling psychologist should know. Counseling Psychologist, 43(4), 508–557.
537 Giacomucci, S. (2021). Social work, sociometry, and psychodrama: Experiential approaches for group therapists, community leaders, and social workers. Springer.
538 Richmond, C., Smock Jordan, S., Bischof, G., & Sauer, E. (2014). Effects of solution-focused versus problem-focused intake questions on pre-treatment change. Journal of Systemic Therapies, 33, 33–47.
539 Sanders, M. A. (2021, April 14). Strength-based counseling. Great Lakes ATTC. https://attcnetwork.org/centers/great-lakes-attc/news/strength-based-counseling.
540 Richmond, C., Smock Jordan, S., Bischof, G., & Sauer, E. (2014). Effects of solution-focused versus problem-focused intake questions on pre-treatment change. Journal of Systemic Therapies, 33, 33–47.
541 Henwood, B. F., Derejko, K. S., Couture, J., & Padgett, D. K. (2015). Maslow and mental health recovery: A comparative study of homeless programs for adults with serious mental illness. Administration and Policy in Mental Health, 42(2), 220–228.24518968
542 Addiction Technology Transfer Center Network. (2006). Treatment planning -Part 3: Putting it all together. Addiction Messenger, 9(6).
543 Henwood, B. F., Derejko, K. S., Couture, J., & Padgett, D. K. (2015). Maslow and mental health recovery: A comparative study of homeless programs for adults with serious mental illness. Administration and Policy in Mental Health, 42(2), 220–228.24518968
544 Best, D., Day, E., McCarthy, T., Darlington, I., & Pinchbeck, K. (2008). The hierarchy of needs and care planning in addiction services: What Maslow can tell us about addressing competing priorities? Addiction Research & Theory, 16(4), 305–307.
545 Henwood, B. F., Derejko, K. S., Couture, J., & Padgett, D. K. (2015). Maslow and mental health recovery: A comparative study of homeless programs for adults with serious mental illness. Administration and Policy in Mental Health, 42(2), 220–228.24518968
546 Henwood, B. F., Derejko, K. S., Couture, J., & Padgett, D. K. (2015). Maslow and mental health recovery: A comparative study of homeless programs for adults with serious mental illness. Administration and Policy in Mental Health, 42(2), 220–228.24518968
547 Roos, C. R., Bowen, S., & Kober, H. (2022). The role of self-regulation strategies in recovery from alcohol use disorder. In J. A. Tucker & K. Witkiewitz (Eds.), Dynamic pathways to recovery from alcohol use disorder: Meanings and methods. Cambridge University Press.
548 Ameral, V., & Palm Reed, K. M. (2021). Envisioning a future: Values clarification in early recovery from opioid use disorder. Journal of Substance Abuse Treatment, 121, 108207.33357601
549 Barrett, K., O'Connor, M., & McHugh, L. (2019). A systematic review of values-based psychometric tools within Acceptance and Commitment Therapy (ACT). Psychological Record, 69(4), 457–485.
550 Ameral, V., & Palm Reed, K. M. (2021). Envisioning a future: Values clarification in early recovery from opioid use disorder. Journal of Substance Abuse Treatment, 121, 108207.33357601
551 Ameral, V., & Palm Reed, K. M. (2021). Envisioning a future: Values clarification in early recovery from opioid use disorder. Journal of Substance Abuse Treatment, 121, 108207.33357601
552 Barrett, K., O'Connor, M., & McHugh, L. (2019). A systematic review of values-based psychometric tools within Acceptance and Commitment Therapy (ACT). Psychological Record, 69(4), 457–485.
553 Community Catalyst, Faces & Voices of Recovery, & American Society of Addiction Medicine. (2021). Peers speak out: Priority outcomes for substance use treatment and services..
554 Recovery Research Institute. (2021, August 26). Whose voice counts? Treatment outcomes prioritized by people with substance use challenges and their families. https://www.recoveryanswers.org/research-post/whose-voice-counts-treatment-outcomes-prioritized-people-substance-use-challenges-and-families.
555 Community Catalyst, Faces & Voices of Recovery, & American Society of Addiction Medicine. (2021). Peers speak out: Priority outcomes for substance use treatment and services (Graph 1).
556 Flannery, M. (2017). Self-determination theory: Intrinsic motivation and behavioral change. Oncology Nursing Forum, 44(2), 155–156.28222078
557 DiClemente, C. C., Corno, C. M., Graydon, M. M., Wiprovnick, A. E., & Knoblach, D. J. (2017). Motivational interviewing, enhancement, and brief interventions over the last decade: A review of reviews of efficacy and effectiveness. Psychology of Addictive Behaviors, 31(8), 862–887.29199843
558 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
559 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
560 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
561 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
562 Substance Abuse and Mental Health Services Administration. (n.d.). Peers supporting recovery from substance use disorders. https://www.samhsa.gov/sites/default/files/programs_campaigns/brsstacs/peers-supporting-recovery-substance-use-disorders-2017.pdf.
563 White, W. & Cloud, W. (2008). Recovery capital: A primer for addictions professionals. Counselor, 9(5), 22–27.
564 Sánchez, J., Sahker, E., & Arndt, S. (2020). The Assessment of Recovery Capital (ARC) predicts substance abuse treatment completion. Addictive Behaviors, 102, 106189.31778848
565 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
566 Radcliffe, P., Tompkins, C., Timpson, H., Eckley, L., Sumnall, H., Pendlebury, M., & Hay, G. (2016). “Once you've been there, you're always recovering”: Exploring experiences, outcomes, and benefits of substance misuse recovery. Drugs and Alcohol Today, 16(1), 29–38.
567 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
568 Cloud, W., & Granfield, R. (2008). Conceptualizing recovery capital: Expansion of a theoretical construct. Substance Use & Misuse, 43(12-13), 1971–1986.19016174
569 Neale, J., Vitoratou, S., Finch, E., Lennon, P., Mitcheson, L., Panebianco, D., … Marsden, J. (2016). Development and validation of ‘SURE’: A patient reported outcome measure (PROM) for recovery from drug and alcohol dependence. Drug and Alcohol Dependence, 165, 159–167.27344196
570 Neale, J., Vitoratou, S., Finch, E., Lennon, P., Mitcheson, L., Panebianco, D., Marsden, J. (2016). Development and validation of ‘SURE’: A patient reported outcome measure (PROM) for recovery from drug and alcohol dependence. Drug and Alcohol Dependence, 165, 159–167.27344196
571 Neale, J., Vitoratou, S., Finch, E., Lennon, P., Mitcheson, L., Panebianco, D., Marsden, J. (2016). Development and validation of ‘SURE’: A patient reported outcome measure (PROM) for recovery from drug and alcohol dependence. Drug and Alcohol Dependence, 165, 159–167.27344196
572 Sánchez, J., Sahker, E., & Arndt, S. (2020). The Assessment of Recovery Capital (ARC) predicts substance abuse treatment completion. Addictive Behaviors, 102, 106189.31778848
573 Sánchez, J., Sahker, E., & Arndt, S. (2020). The Assessment of Recovery Capital (ARC) predicts substance abuse treatment completion. Addictive Behaviors, 102, 106189.31778848
574 Vilsaint, C. L., Kelly, J. F., Bergman, B. G., Groshkova, T., Best, D., & White, W. (2017). Development and validation of a Brief Assessment of Recovery Capital (BARC-10) for alcohol and drug use disorder. Drug and Alcohol Dependence, 177, 71–76.28578224
575 Vilsaint, C. L., Kelly, J. F., Bergman, B. G., Groshkova, T., Best, D., & White, W. (2017). Development and validation of a Brief Assessment of Recovery Capital (BARC-10) for alcohol and drug use disorder. Drug and Alcohol Dependence, 177, 71–76.28578224
576 Best, D., Sondhi, A., Brown, L., Nisic, M., Nagelhout, G. E., Martinelli, T., & Vanderplasschen, W. (2021). The Strengths and Barriers Recovery Scale (SABRS): Relationships matter in building strengths and overcoming barriers. Frontiers in Psychology, 12, 663447.33841289
577 Bowen, E. A., Scott, C. F., Irish, A., & Nochajski, T. H. (2020). Psychometric properties of the Assessment of Recovery Capital (ARC) instrument in a diverse low-income sample. Substance Use & Misuse, 55(1), 108–118.31519121
578 Bowen, E. A., Scott, C. F., Irish, A., & Nochajski, T. H. (2020). Psychometric properties of the Assessment of Recovery Capital (ARC) instrument in a diverse low-income sample. Substance Use & Misuse, 55(1), 108–118.31519121
579 Bowen, E., Irish, A., LaBarre, C., Capozziello, N., Nochajski, T., & Granfield, R. (2022). Qualitative insights in item development for a comprehensive and inclusive measure of recovery capital. Addiction Research & Theory, 1–11.
580 American Psychological Association. (n.d.). Unconditional positive regard. In APA dictionary of psychology. https://dictionary.apa.org/unconditional-positive-regard.
581 Farber, B. A., Suzuki, J. Y., & Lynch, D. A. (2018). Positive regard and psychotherapy outcome: A meta-analytic review. Psychotherapy, 55(4), 411.30335454
582 Gutierrez, D., Butts, C. M., Lamberson, K. A., & Lassiter, P. S. (2019). Examining the contributions of trait emotional intelligence on addiction counselor burnout (p. 60). Journal of Addictions & Offender Counseling, 40(1), 52–64.
583 Farber, B. A., Suzuki, J. Y., & Lynch, D. A. (2018). Positive regard and psychotherapy outcome: A meta-analytic review. Psychotherapy, 55(4), 411.30335454
584 Watson, J. C., & Sharbanee, J. M. (2022). Emotion-focused therapy-case conceptualization and treatment: Adults. In G. J. G. Asmundson (Ed.), Comprehensive clinical psychology (2nd ed., pp. 105–128). Elsevier.
585 Watson, J. C., & Sharbanee, J. M. (2022). Emotion-focused therapy-case conceptualization and treatment: Adults. In G. J. G. Asmundson (Ed.), Comprehensive clinical psychology (2nd ed., pp. 105–128). Elsevier.
586 Matto, H., & Seshaiyer, P. (2018). Harnessing the power of the recovering brain to promote recovery commitment and reduce relapse risk. Journal for the Society for Social Work and Research, 9(2), 341–358.
587 Matto, H. (2015). Biobehavioral response redirection: Innovations to activate personalized recovery cues and decrease relapse risk. Journal of Social Work Practice in the Addictions, 15, 450–453.
588 Matto, H., & Seshaiyer, P. (2018). Harnessing the power of the recovering brain to promote recovery commitment and reduce relapse risk. Journal for the Society for Social Work and Research, 9(2), 341–358.
589 Matto, H., & Seshaiyer, P. (2018). Harnessing the power of the recovering brain to promote recovery commitment and reduce relapse risk. Journal for the Society for Social Work and Research, 9(2), 341–358.
590 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
591 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
592 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
593 Page, J., & Townsend, J. (2018). The role of recreation and recreational therapists in developing a recovery-oriented identity for people with substance use disorders. Alcoholism Treatment Quarterly, 36(2), 238–254.
594 American Addiction Centers. (2022). Addiction as a coping mechanism and healthy alternatives. https://americanaddictioncenters.org/sobriety-guide/coping-mechanism.
595 American Addiction Centers. (2022). Addiction as a coping mechanism and healthy alternatives. https://americanaddictioncenters.org/sobriety-guide/coping-mechanism.
596 Shircliff, K., Liu, M., Prestigiacomo, C., Fry, M., Ladd, K., Gilbert, M. K., … Cyders, M. A. (2022). Mixed methods prospective findings of the initial effects of the US COVID-19 pandemic on individuals in recovery from substance use disorder. PloS One, 17(7), e0270582.
597 Pinhasi-Vittorio, L. (2018). Writing, sharing, and healing: The interplay of literacy in the healing journey of the recovering from substance abuse. Journal of Poetry Therapy, 31(4), 209–223.
598 Santa Maria, D., Padhye, N., Yang, Y., Gallardo, K., Santos, G. M., Jung, J., & Businelle, M. (2018). Drug use patterns and predictors among homeless youth: Results of an ecological momentary assessment. American Journal of Drug and Alcohol Abuse, 44(5), 551–560.29286835
599 LeCocq, M. R., Randall, P. A., Besheer, J., & Chaudhri, N. (2020). Considering drug-associated contexts in substance use disorders and treatment development. Neurotherapeutics, 17(1), 43–54.31898285
600 Carpenter, K. M., & Kosanke, N. (n.d.) Developing a behavioral treatment protocol in conjunction with MAT. http://pcssnow.org/wp-content/uploads/2015/02/Developing-a-Behavioral-Treatment-Protocol-in-conjunction-with-MAT.pdf.
601 Kruger, E. S., Serier, K. N., Pfund, R. A., McKay, J. R., & Witkiewitz, K. (2021). Integrative data analysis of self-efficacy in 4 clinical trials for alcohol use disorder. Alcoholism, Clinical and Experimental Research, 45(11), 2347–2356.34523721
602 Kruger, E. S., Serier, K. N., Pfund, R. A., McKay, J. R., & Witkiewitz, K. (2021). Integrative data analysis of self-efficacy in 4 clinical trials for alcohol use disorder. Alcoholism, Clinical and Experimental Research, 45(11), 2347–2356.34523721
603 Worley J. (2017). Recovery in substance use disorders: What to know to inform practice. Issues in Mental Health Nursing, 38(1), 80–91.27901625
604 Müller, A., Znoj, H., & Moggi, F. (2019). How are self-efficacy and motivation related to drinking five years after residential treatment? A longitudinal multicenter study. European Addiction Research, 25(5), 213–223.31112984
605 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
606 Kruger, E. S., Serier, K. N., Pfund, R. A., McKay, J. R., & Witkiewitz, K. (2021). Integrative data analysis of self-efficacy in 4 clinical trials for alcohol use disorder. Alcoholism, Clinical and Experimental Research, 45(11), 2347–2356.34523721
607 Worley, J. (2017). Recovery in substance use disorders: What to know to inform practice. Issues in Mental Health Nursing, 38(1), 80–91.27901625
608 Worley, J. (2017). Recovery in substance use disorders: What to know to inform practice. Issues in Mental Health Nursing, 38(1), 80–91.27901625
609 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
610 Luciano, M. T., McDevitt-Murphy, M. E., Murphy, J. G., Zakarian, R. J., & Olin, C. (2022). Open trial of a personalized feedback intervention and substance-free activity supplement for veterans with PTSD and hazardous drinking. Journal of Behavioral and Cognitive Therapy, 32(2), 136–144.35872748
611 Murphy, J. G., Dennhardt, A. A., Martens, M. P., Borsari, B., Witkiewitz, K., & Meshesha, L. Z. (2019). A randomized clinical trial evaluating the efficacy of a brief alcohol intervention supplemented with a substance-free activity session or relaxation training. Journal of Consulting and Clinical Psychology, 87(7), 657.31070386
612 Daughters, S. B., Magidson, J. F., Anand, D., Seitz-Brown, C. J., Chen, Y., & Baker, S. (2018). The effect of a behavioral activation treatment for substance use on post-treatment abstinence: A randomized controlled trial. Addiction (Abingdon, England), 113(3), 535–544.28963853
613 Magidson, J. F., Kleinman, M. B., Bradley, V., Anvari, M. S., Abidogun, T. M., Belcher, A. M., … Felton, J. W. (2022). Peer recovery specialist-delivered, behavioral activation intervention to improve retention in methadone treatment: Results from an open-label, Type 1 hybrid effectiveness-implementation pilot trial. International Journal on Drug Policy, 108, 103813. Advance online publication.35932644
614 Murphy, J. G., Dennhardt, A. A., Martens, M. P., Borsari, B., Witkiewitz, K., & Meshesha, L. Z. (2019). A randomized clinical trial evaluating the efficacy of a brief alcohol intervention supplemented with a substance-free activity session or relaxation training. Journal of Consulting and Clinical Psychology, 87(7), 657.
615 Luciano, M. T., McDevitt-Murphy, M. E., Murphy, J. G., Zakarian, R. J., & Olin, C. (2022). Open trial of a personalized feedback intervention and substance-free activity supplement for veterans with PTSD and hazardous drinking. Journal of Behavioral and Cognitive Therapy, 32(2), 136–144.35872748
616 Murphy, J. G., Dennhardt, A. A., Martens, M. P., Borsari, B., Witkiewitz, K., & Meshesha, L. Z. (2019). A randomized clinical trial evaluating the efficacy of a brief alcohol intervention supplemented with a substance-free activity session or relaxation training. Journal of Consulting and Clinical Psychology, 87(7), 657.31070386
617 Field, M., Heather, N., Murphy, J. G., Stafford, T., Tucker, J. A., & Witkiewitz, K. (2020). Recovery from addiction: Behavioral economics and value-based decision making. Psychology of Addictive Behaviors: Journal of the Society of Psychologists in Addictive Behaviors, 34(1), 182–193.31599604
618 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
619 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
620 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
621 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
622 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
623 Acuff, S. F., Tucker, J. A., & Murphy, J. G. (2021). Behavioral economics of substance use: Understanding and reducing harmful use during the COVID-19 pandemic. Experimental and Clinical Psychopharmacology, 29(6), 739–749.33166163
624 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. https://store.samhsa.gov/product/SAMHSA-s-Working-Definition-of-Recovery/PEP12-RECDEF.
625 Substance Abuse and Mental Health Services Administration. (2022). Recovery and recovery support. https://www.samhsa.gov/find-help/recovery.
626 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. https://store.samhsa.gov/product/SAMHSA-s-Working-Definition-of-Recovery/PEP12-RECDEF.
627 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
628 Graser, Y., Stutz, S., Rösner, S., Moggi, F., & Soravia, L. M. (2021). Telephone-and text message-based continuing care after residential treatment for alcohol use disorder: A randomized clinical multicenter study. Alcoholism, Clinical and Experimental Research, 45(1), 224–233.33245589
629 Krentzman, A. R. (2013). Review of the application of positive psychology to substance use, addiction, and recovery research. Psychology of Addictive Behaviors, 27(1), 151–165.22985057
630 McKay, J. R. (2021). Impact of continuing care on recovery from substance use disorder. Alcohol Research: Current Reviews, 41(1), 01.33500871
631 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
632 Scott, C. K., Grella, C. E., Dennis, M. L., & Nicholson, L. (2018). Linking individuals with substance use disorders (SUDs) in primary care to SUD treatment: The Recovery Management Checkups-Primary Care (RMC-PC) pilot study. Journal of Behavioral Health Services & Research, 45(2), 160–173.29181779
633 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
634 Kelly, J. F., Greene, M. C., Bergman, B. G., White, W. L., & Hoeppner, B. B. (2019). How many recovery attempts does it take to successfully resolve an alcohol or drug problem? Estimates and correlates from a national study of recovering U.S. adults. Alcoholism, Clinical and Experimental Research, 43(7), 1533–1544.31090945
635 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
636 Williams, I. L., & Bonner, E. (2020). Patient termination as the ultimate failure of addiction treatment: Reframing administrative discharge as clinical abandonment. Journal of Social Work Values and Ethics, 17(1), 35–46.
637 Kelly, J. F., Greene, M. C., Bergman, B. G., White, W. L., & Hoeppner, B. B. (2019). How many recovery attempts does it take to successfully resolve an alcohol or drug problem? Estimates and correlates from a national study of recovering U.S. adults. Alcoholism, Clinical and Experimental Research, 43(7), 1533–1544.31090945
638 Guenzel, N., & MChargue, D. (2021, July 18). Addiction relapse prevention [StatPearls]. StatPearls Publishing.
639 McCabe, S. E., West, B. T., Strobbe, S., & Boyd, C. J. (2018). Persistence/recurrence of and remission from DSM-5 substance use disorders in the United States: Substance-specific and substance-aggregated correlates. Journal of Substance Abuse Treatment, 93, 38–48.30126540
640 Paquette, C. E., Daughters, S. B., & Witkiewitz, K. (2022). Expanding the continuum of substance use disorder treatment: Nonabstinence approaches. Clinical Psychology Review, 91, 102110.34864497
641 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
642 Melemis, S. M. (2015). Relapse prevention and the five rules of recovery. Yale Journal of Biology and Medicine, 88, 325–332.26339217
643 Reesor, L., Vaughan, E. M., Hernandez, D. C., & Johnston, C. A. (2017). Addressing outcomes expectancies in behavior change. American Journal of Lifestyle Medicine, 11(6), 430–432.29302249
644 Montes, K. S., Witkiewitz, K., Pearson, M. R., & Leventhal, A. M. (2019). Alcohol, tobacco, and marijuana expectancies as predictors of substance use initiation in adolescence: A longitudinal examination. Psychology of Addictive Behaviors, 33(1), 26–34.30407027
645 Reesor, L., Vaughan, E. M., Hernandez, D. C., & Johnston, C. A. (2017). Addressing outcomes expectancies in behavior change. American Journal of Lifestyle Medicine, 11(6), 430–432.29302249
646 Recovery Research Institute. (n.d.). Meditation helps heal the brain during opioid addiction treatment. https://www.recoveryanswers.org/research-post/mind-synaptic-gap-can-mindfulness-meditation-help-heal-brain-opioid-addiction-treatment/.
647 Reesor, L., Vaughan, E. M., Hernandez, D. C., & Johnston, C. A. (2017). Addressing outcomes expectancies in behavior change. American Journal of Lifestyle Medicine, 11(6), 430–432.29302249
648 Reesor, L., Vaughan, E. M., Hernandez, D. C., & Johnston, C. A. (2017). Addressing outcomes expectancies in behavior change. American Journal of Lifestyle Medicine, 11(6), 430–432.29302249
649 Reesor, L., Vaughan, E. M., Hernandez, D. C., & Johnston, C. A. (2017). Addressing outcomes expectancies in behavior change. American Journal of Lifestyle Medicine, 11(6), 430–432.29302249
650 Gutierrez, D., Dorais, S., & Goshorn, J. R. (2020). Recovery as life transformation: Examining the relationships between recovery, hope, and relapse. Substance Use & Misuse, 55(12), 1949–1957.32567447
651 Gutierrez, D., Dorais, S., & Goshorn, J. R. (2020). Recovery as life transformation: Examining the relationships between recovery, hope, and relapse. Substance Use & Misuse, 55(12), 1949–1957.32567447
652 Berman, B. M., & Kurlancheek, K. (2021). The choice point model of acceptance and commitment therapy with inpatient substance use and co-occurring populations: A pilot study. Frontiers in Psychology, 12, 758356.34777161
653 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
654 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
655 Bradford Health Services. (2022). HALT: The dangers of hunger, anger, loneliness, and tiredness. https://bradfordhealth.com/halt-hunger-anger-loneliness-tiredness/.
656 Marcovitz, D. E., McHugh, K. R., Roos, C., West, J. J., & Kelly, J. (2020). Overlapping mechanisms of recovery between professional psychotherapies and Alcoholics Anonymous. Journal of Addiction Medicine, 14(5), 367–375.32058337
657 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
658 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
659 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
660 Kelly, J. F., & Greene, M. C. (2014). Beyond motivation: Initial validation of the commitment to sobriety scale. Journal of Substance Abuse Treatment, 46(2), 257–263.23953168
661 Kelly, J. F., & Greene, M. C. (2014). Beyond motivation: Initial validation of the commitment to sobriety scale. Journal of Substance Abuse Treatment, 46(2), 257–263.23953168
662 Kelly, J. F., & Greene, M. C. (2014). Beyond motivation: Initial validation of the commitment to sobriety scale. Journal of Substance Abuse Treatment, 46(2), 257–263.23953168
663 Kelly, J. F., & Greene, M. C. (2014). Beyond motivation: Initial validation of the commitment to sobriety scale. Journal of Substance Abuse Treatment, 46(2), 257–263.23953168
664 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
665 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
666 Dickson-Gomez, J., Weeks, M., Green, D., Boutouis, S., Galletly, C., & Christenso, E. (2022). Insurance barriers to substance use disorder treatment after passage of mental health and addiction parity laws and the Affordable Care Act: A qualitative analysis. Drug and Alcohol Dependence Reports, 3, 100053.35783993
667 Dickson-Gomez, J., Weeks, M., Green, D., Boutouis, S., Galletly, C., & Christenso, E. (2022). Insurance barriers to substance use disorder treatment after passage of mental health and addiction parity laws and the Affordable Care Act: A qualitative analysis. Drug and Alcohol Dependence Reports, 3, 100053.35783993
668 Dickson-Gomez, J., Weeks, M., Green, D., Boutouis, S., Galletly, C., & Christenso, E. (2022). Insurance barriers to substance use disorder treatment after passage of mental health and addiction parity laws and the Affordable Care Act: A qualitative analysis. Drug and Alcohol Dependence Reports, 3, 100053.35783993
669 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem. National Academy of Medicine. https://nam.edu/guide-for-future-directions-for-the-addiction-and-oud-treatment-ecosystem/.
670 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem. National Academy of Medicine. https://nam.edu/guide-for-future-directions-for-the-addiction-and-oud-treatment-ecosystem/.
671 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
672 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem. National Academy of Medicine. https://nam.edu/guide-for-future-directions-for-the-addiction-and-oud-treatment-ecosystem/.
673 Partnership to End Addiction. (2020). Spotlight on legislation limiting the use of prior authorization for substance use disorder services and medications. https://drugfree.org/reports/spotlight-on-prior-authorization/.
674 Saloner, B., Bandara, S., Bachhuber, M. & Barry, C. L. (2017). Insurance coverage and treatment use under the Affordable Care Act among adults with mental and substance use disorders. Psychiatric Services, 68, 542–548.28093059
675 Dickson-Gomez, J., Weeks, M., Green, D., Boutouis, S., Galletly, C., & Christenso, E. (2022). Insurance barriers to substance use disorder treatment after passage of mental health and addiction parity laws and the Affordable Care Act: A qualitative analysis. Drug and Alcohol Dependence Reports, 3, 100053.35783993
676 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem. National Academy of Medicine. https://nam.edu/guide-for-future-directions-for-the-addiction-and-oud-treatment-ecosystem/.
677 Waller, R. C., Clark, K. J., Woodruff, A., Glossa, J., & Ostrovsky, A. (2021). Guide for future directions for the addiction and OUD treatment ecosystem. National Academy of Medicine. https://nam.edu/guide-for-future-directions-for-the-addiction-and-oud-treatment-ecosystem/.
678 Broderick, S. (2017, June 26). Addiction & the criminal justice system. Recovery Research Institute. https://www.recoveryanswers.org/blog/recovery-answers-from-an-criminal-justice-public-policy-expert/.
679 HealthCare.gov. (n.d.). Health coverage for incarcerated people. U.S. Centers for Medicare & Medicaid Services. https://www.healthcare.gov/incarcerated-people/.
680 Office of the Surgeon General. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health. U.S. Department of Health and Human Services.
681 Federal Register. (2013, November 11). Final rules under the Paul Wellstone and Pete Domenici Mental Health Parity and Addiction Equity Act of 2008; technical amendment to external review for multi-state plan program (pp. 68239–68296). 78 FR 68239. National Archives. https://www.federalregister.gov/documents/2013/11/13/2013-27086/final-rules-under-the-paul-wellstone-and-pete-domenici-mental-health-parity-and-addiction-equity-act.
682 DiClemente, C. C., Norwood, A. E., Gregory, W. H., Travaglini, L., Graydon, M. M., & Corno, C. M. (2016). Consumer-centered, collaborative, and comprehensive care: The core essentials of recovery-oriented system of care. Journal of Addictions Nursing, 27(2), 94–100.27272993
683 Bitting, S., Nash, A., & Ochoa, A. (2016). Houston Recovery Initiative: A rich case study of building recovery communities one voice at a time. Journal of Addictions Nursing, 27(2), 120–126.27272996
684 University of Texas at Austin, Addiction Research Institute. (2018). Recovery support services project: Fiscal year 2017 final evaluation report. South Southwest ATTC. https://attcnetwork.org/centers/south-southwest-attc/product/recovery-support-services-project-fiscal-year-2017-final.
685 Ashford, R. D., Brown, A. M., Ryding, R., & Curtis, B. (2020). Building recovery ready communities: The recovery ready ecosystem model and community framework. Addiction Research & Theory, 28(1), 1–11.
686 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01p-005. Substance Abuse and Mental Health Services Administration.
687 Substance Abuse and Mental Health Services Administration. (2018). Key substance use and mental health indicators in the United States: Results from the 2017 National Survey on Drug Use and Health. HHS Publication No. (SMA) 18-5068, NSDUH Series H-53. Center for Behavioral Health Statistics and Quality, Substance Abuse and Mental Health Services Administration.
688 Substance Abuse and Mental Health Services Administration. (2022). Key substance use and mental health indicators in the United States: Results from the 2021 National Survey on Drug Use and Health. HHS Publication No. PEP22-07-01-005. Substance Abuse and Mental Health Services Administration.
689 National Institute on Drug Abuse. (2020). Addressing the stigma that surrounds addiction [Blog post]. https://nida.nih.gov/about-nida/noras-blog/2020/04/addressing-stigma-surrounds-addiction.
690 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
691 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
692 National Harm Reduction Coalition. (2020). Principles of harm reduction. https://harmreduction.org/about-us/principles-of-harm-reduction/.
693 Fentress, T., Wald, S., Brah, A., Leemon, G., Reyes, R., Alkhamees, F., … Collins, S. E. (2021). Dual study describing patient-driven harm reduction goal-setting among people experiencing homelessness and alcohol use disorder. Experimental and Clinical Psychopharmacology, 29(3), 261–271.34264737
694 Substance Abuse and Mental Health Services Administration. (2023). Harm reduction framework. https://www.samhsa.gov/find-help/harm-reduction/framework.
695 Huhn, A. S., & Gipson, C. D. (2021). Promoting harm reduction as a treatment outcome in substance use disorders. Experimental and Clinical Psychopharmacology, 29(3), 217–218.34264733
696 Hyshka, E., Morris, H., Anderson-Baron, J., Nixon, L., Dong, K., & Salvalaggio, G. (2019). Patient perspectives on a harm reduction-oriented addiction medicine consultation team implemented in a large acute care hospital. Drug and Alcohol Dependence, 204, 107523.31541875
697 Ashford, R. D., Curtis, B., & Brown, A. M. (2018). Peer-delivered harm reduction and recovery support services: Initial evaluation from a hybrid recovery community drop-in center and syringe exchange program. Harm Reduction Journal, 15(1), 52.30348170
698 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
699 U.S. Department of Health and Human Services. (n.d.). Overdose prevention strategy: Harm reduction. https://www.hhs.gov/overdose-prevention/harm-reduction.
700 Hyshka, E., Morris, H., Anderson-Baron, J., Nixon, L., Dong, K., & Salvalaggio, G. (2019). Patient perspectives on a harm reduction-oriented addiction medicine consultation team implemented in a large acute care hospital. Drug and Alcohol Dependence, 204, 107523.31541875
701 Ashford, R. D., Curtis, B., & Brown, A. M. (2018). Peer-delivered harm reduction and recovery support services: Initial evaluation from a hybrid recovery community drop-in center and syringe exchange program. Harm Reduction Journal, 15(1), 52.30348170
702 Magwood, O., Salvalaggio, G., Beder, M., Kendall, C., Kpade, V., Daghmach, W., … Pottie, K. (2020). The effectiveness of substance use interventions for homeless and vulnerably housed persons: A systematic review of systematic reviews on supervised consumption facilities, managed alcohol programs, and pharmacological agents for opioid use disorder. PloS One, 15(1), e0227298.31945092
703 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
704 Substance Abuse and Mental Health Services Administration. (2023). Harm reduction framework. https://www.samhsa.gov/find-help/harm-reduction/framework.
705 Stock, C., Geier, M., & Nowicki, K. (2018). Harm reduction strategies for people who inject drugs: Considerations for pharmacists. https://www.opioidlibrary.org/wp-content/uploads/2019/06/CPNPHarmReductPharmacists.pdf.
706 Capizzi, J., Leahy, J., Wheelock, H., Garcia, J., Strnad, L., Sikka, M., … Menza, T W. (2020). Population-based trends in hospitalizations due to injection drug use-related serious bacterial infections, Oregon, 2008 to 2018. PLoS One, 15(11), e0242165.33166363
707 Chawla, N., & Sarkar, S. (2019). Defining “highrisk sexual behavior” in the context of substance use. Journal of Psychosexual Health, 1(1), 26–31.
708 Stock, C., Geier, M., & Nowicki, K. (2018). Harm reduction strategies for people who inject drugs: Considerations for pharmacists. https://www.opioidlibrary.org/wp-content/uploads/2019/06/CPNPHarmReductPharmacists.pdf.
709 Centers for Disease Control and Prevention. (2019). Summary of information on the safety and effectiveness of syringe services programs (SSPs). https://www.cdc.gov/ssp/syringe-services-programs-summary.html.
710 Centers for Disease Control and Prevention. (2019). Summary of information on the safety and effectiveness of syringe services programs (SSPs). https://www.cdc.gov/ssp/syringe-services-programs-summary.html.
711 Stock, C., Geier, M., & Nowicki, K. (2018). Harm reduction strategies for people who inject drugs: Considerations for pharmacists. https://www.opioidlibrary.org/wp-content/uploads/2019/06/CPNP_HarmReductPharmacists.pdf.
712 Centers for Disease Control and Prevention. (2019). Syringe services programs (SSPs) FAQs. https://www.cdc.gov/ssp/syringe-services-programs-faq.html.
713 Centers for Disease Control and Prevention. (2019). Syringe services programs (SSPs) FAQs. https://www.cdc.gov/ssp/syringe-services-programs-faq.html.
714 Centers for Disease Control and Prevention. (2017). Reducing harms from injection drug use & opioid use disorder with syringe services programs. https://www.cdc.gov/hiv/pdf/risk/cdchiv-fs-syringe-services.pdf.
715 Stock, S., Geier, M., & Nowicki, K. (2019). Harm reduction strategies for people who inject drugs: Considerations for pharmacists. https://www.opioidlibrary.org/wp-content/uploads/2019/06/CPNP_HarmReductPharmacists.pdf.
716 Centers for Disease Control and Prevention. (2020). Hepatitis C. https://www.cdc.gov/hepatitis/hcv/index.htm.
717 Centers for Disease Control and Prevention. (2020). Hepatitis C. https:/www.cdc.gov/hepatitis/hcv/index.htm (https://www.cdc.gov/hepatitis/hcv/index.htm).
718 National Harm Reduction Coalition. (2021). Hepatitis C: Basics for people who use drugs (PWUD). https://harmreduction.org/issues/hepatitis-c/basics-brochure/.
719 Centers for Disease Control and Prevention. (2020). Hepatitis C. https://www.cdc.gov/hepatitis/h¿v/index.htm.
720 National Harm Reduction Coalition. (2021). Hepatitis C: Basics for people who use drugs (PWUD). https://harmreduction.org/issues/hepatitis-c/basics-brochure/.
721 National Harm Reduction Coalition. (n.d.). Hepatitis C. https://harmreduction.org/issues/hepatitis-c/#:~:text=Hepatitis%20C%20Prevention%20Means%20Usingfprograms%20(SSPs)%20in%20the%20U.S.
722 National Harm Reduction Coalition. (2021). Hepatitis C: Basics for people who use drugs (PWUD). https://harmreduction.org/issues/hepatitis-c/basics-brochure/.
723 National Institute on Drug Abuse. (2022). Naloxone DrugFacts. https://nida.nih.gov/publications/drugfacts/naloxone.
724 U.S. Food and Drug Administration. (2023). FDA approves first over-the-counter naloxone nasal spray. https://www.fda.gov/news-events/press-announcements/fda-approves-first-over-counter-naloxone-nasal-spray.
725 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
726 National Institute on Drug Abuse. (2022). Naloxone DrugFacts. https://nida.nih.gov/publications/drugfacts/naloxone.
727 Substance Abuse and Mental Health Services Administration. (2022). Naloxone. https://www.samhsa.gov/medicatiQn-assisted-treatment/medications-counseling-related-conditions/naloxone.
728 Food and Drug Administration. (2023). Naloxone and nalmefene. https://www.fda.gov/drugs/postmarket-drug-safety-information-patients-and-providers/information-about-naloxone-and-nalmefene.
729 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
730 Peet, E. D., Powell, D., & Pacula, R. L. (2022). Trends in out-of-pocket costs for naloxone by drug brand and payer in the US, 2010-2018. JAMA Health Forum, 3(8), e222663.36200636
731 Goldman, J. E., Waye, K. M., Periera, K. A., Krieger, M. S., Yedinak, J. L., & Marshall, B. (2019). Perspectives on rapid fentanyl test strips as a harm reduction practice among young adults who use drugs: A qualitative study. Harm Reduction Journal, 16(1), 3.30621699
732 National Institute on Drug Abuse. (2021). Is naloxone accessible? In Medications to treat opioid use disorder research report. https://nida.nih.gov/download/21349/medications-to-treat-opioid-use-disorder-research-report.pdf?v=99088f7584dac93ddcfa98648065bfbe.
733 National Institute on Drug Abuse. (2021). Is naloxone accessible? In Medications to treat opioid use disorder research report. https://nida.nih.gov/download/21349/medications-to-treat-opioid-use-disorder-research-report.pdf?v=99088f7584dac93ddcfa98648065bfbe.
734 Enteen, L., Bauer, J., McLean, R., Wheeler, E., Huriaux, E., Kral, A. H., & Bamberger, J. D. (2010). Overdose prevention and naloxone prescription for opioid users in San Francisco. Journal of Urban Health, 87(6), 931–941.20967505
735 Centers for Disease Control and Prevention. (2022). Fentanyl facts. https://www.cdc.gov/stopoverdose/fentanyl/.
736 Wilson, N., Kariisa, M., Seth, P., Smith, H. & Davis, N. L. (2020). Drug and opioid-involved overdose deaths — United States, 2017-2018. MMWR, 69, 290–297.32191688
737 Centers for Disease Control and Prevention. (2022). Fentanyl facts. https://www.cdc.gov/stopoverdose/fentanyl/.
738 Centers for Disease Control and Prevention. (2022). Fentanyl facts. https://www.cdc.gov/stopoverdose/fentanyl/.
739 Goldman, J. E., Waye, K. M., Periera, K. A., Krieger, M. S., Yedinak, J. L., & Marshall, B. (2019). Perspectives on rapid fentanyl test strips as a harm reduction practice among young adults who use drugs: A qualitative study. Harm Reduction Journal, 16(1), 3.30621699
740 Centers for Disease Control and Prevention. (2022). Fentanyl facts. https://www.cdc.gov/stopoverdose/fentanyl.
741 Goldman, J. E., Waye, K. M., Periera, K. A., Krieger, M. S., Yedinak, J. L., & Marshall, B. (2019). Perspectives on rapid fentanyl test strips as a harm reduction practice among young adults who use drugs: A qualitative study. Harm Reduction Journal, 16(1), 3.30621699
742 Substance Abuse and Mental Health Services Administration. (2021). Federal grantees may now use funds to purchase fentanyl test strips. https://www.samhsa.gov/newsroom/press-announcements/202104070200.
743 Stock, C., Geier, M., & Nowicki, K. (2018). Harm reduction strategies for people who inject drugs: Considerations for pharmacists. https://www.opioidlibrary.org/wp-content/uploads/2019/06/CPNP_HarmReductPharmacists.pdf.
744 Centers for Disease Control and Prevention. (2023). What should you know about xylazine. https://www.cdc.gov/drugoverdose/deaths/other-drugs/xylazine/faq.html.
745 HIV.gov. (2018). Substance use and HIV risk. https://www.hiv.gov/hiv-basics/hiv-prevention/reducing-risk-from-alcohol-and-drug-use/substance-use-and-hiv-risk.
746 Iversen, J., Long, P., Lutnick, A., & Maher, L. (2021). Patterns and epidemiology of illicit drug use among sex workers globally: A systematic review. In S. M. Goldenberg, R. Morgan Thomas, A. Forbes, & S. Baral (Eds.), Sex work, health, and human rights: Global inequities, challenges, and opportunities for action (p. 95–118). Springer.
747 Iversen, J., Long, P., Lutnick, A., & Maher, L. (2021). Patterns and epidemiology of illicit drug use among sex workers globally: A systematic review. In S. M. Goldenberg, R. Morgan Thomas, A. Forbes, & S. Baral (Eds.), Sex work, health, and human rights: Global inequities, challenges, and opportunities for action (p. 95–118). Springer.
748 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
749 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/fínd-help/harm-reduction.
750 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/fínd-help/harm-reduction.
751 HIV.gov. (2022). Pre-exposure prophylaxis. https://www.hiv.gov/hiv-basics/hiv-prevention/using-hiv-medication-to-reduce-risk/pre-exposure-prophylaxis.
752 HIV.gov. (2021). Post-exposure prophylaxis. https://www.hiv.gov/hiv-basics/hiv-prevention/using-hiv-medication-to-reduce-risk/post-exposure-prophylaxis.
753 Owens, L., Gilmore, K., Terplan, M., Prager, S., & Micks, E. (2020). Providing reproductive health services for women who inject drugs: A pilot program. Harm Reduction Journal, 17(1), 47.
754 Owens, L., Gilmore, K., Terplan, M., Prager, S., & Micks, E. (2020). Providing reproductive health services for women who inject drugs: A pilot program. Harm Reduction Journal, 17(1), 47.32664931
755 Stancil, S. L., Miller, M. K., Duello, A., Finocchario-Kessler, S., Goggin, K., Winograd, R. P., & Hurley, E. A. (2021). Long-acting reversible contraceptives (LARCs) as harm reduction: A qualitative study exploring views of women with histories of opioid misuse. Harm Reduction Journal, 18(1), 83.
756 Centers for Disease Control and Prevention. (2022). Condom distribution structural intervention (CDSI). https://www.cdc.gov/hiv/effective-interventions/prevent/condom-distribution-programs/index.html.
757 Centers for Disease Control and Prevention. (2019). Condom distribution structural intervention (CDSI). https://www.cdc.gov/hiv/effective-interventions/prevent/condom-distribution-programs/index.html.
758 Peterson, R., Kramer, M. P., Pinto, D., De Leon, A. N., Leary, A. V., Marin, A. A., … Dvorak, R. D. (2021). A comprehensive review of measures of protective behavioral strategies across various risk factors and associated PBS-related interventions. Experimental and Clinical Psychopharmacology, 29(3), 236–250.34264735
759 Pearson, M. R. (2013). Use of alcohol protective behavioral strategies among college students: A critical review. Clinical Psychology Review, 33(8), 1025–1040.24036089
760 Peterson, R., Kramer, M. P., Pinto, D., De Leon, A. N., Leary, A. V., Marin, A. A., … Dvorak, R. D. (2021). A comprehensive review of measures of protective behavioral strategies across various risk factors and associated PBS-related interventions. Experimental and Clinical Psychopharmacology, 29(3), 236–250.34264735
761 Tyler, K. A., Schmitz, R. M., Ray, C. M., Adams, S. A., & Simons, L. G. (2018). The role of protective behavioral strategies, social environment, and housing type on heavy drinking among college students. Substance Use & Misuse, 53(5), 724–733.28952844
762 Bravo, A. J., Anthenien, A. M., Prince, M. A., Pearson, M. R., & Marijuana Outcomes Study Team. (2017). Marijuana protective behavioral strategies as a moderator of the effects of risk/protective factors on marijuana-related outcomes. Addictive Behaviors, 69, 14–21.28110137
763 Fentress, T., Wald, S., Brah, A., Leemon, G., Reyes, R., Alkhamees, F., … Collins, S. E. (2021). Dual study describing patient-driven harm reduction goal-setting among people experiencing homelessness and alcohol use disorder. Experimental and Clinical Psychopharmacology, 29(3), 261–271.34264737
764 Harding, R. W., Wagner, K. T., Fiuty, P., Smith, K. P., Page, K., & Wagner, K. D. (2022). “It's called overamping”: Experiences of overdose among people who use methamphetamine. Harm Reduction Journal, 19(1), 1–11.34996466
765 National Harm Reduction Coalition. (2020). Stimulant overamping basics: Training guide. https://harmreduction.org/issues/overdose-prevention/overview/stimulant-overamping-basics/what-is-overamping/.
766 North Carolina Harm Reduction Coalition. (2023). Speed overdosing (overamping). https://www.nchrc.org/naloxone-od-prevention-2/speed-overdose-overamping/.
767 Harding, R. W., Wagner, K. T., Fiuty, P., Smith, K. P., Page, K., & Wagner, K. D. (2022). “It's called overamping”: Experiences of overdose among people who use methamphetamine. Harm Reduction Journal, 19(1), 1–11.34996466
768 National Harm Reduction Coalition. (2020). Stimulant overamping basics: Training guide. https://harmreduction.org/issues/overdose-prevention/overview/stimulant-overamping-basics/what-is-overamping/.
769 National Harm Reduction Coalition. (2020). Stimulant overamping basics: Training guide. https://harmreduction.org/issues/overdose-prevention/overview/stimulant-overamping-basics/what-is-overamping/.
770 Fentress, T., Wald, S., Brah, A., Leemon, G., Reyes, R., Alkhamees, F., … Collins, S. E. (2021). Dual study describing patient-driven harm reduction goal-setting among people experiencing homelessness and alcohol use disorder. Experimental and Clinical Psychopharmacology, 29(3), 261–271.34264737
771 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
772 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
773 Substance Abuse and Mental Health Services Administration. (2022). Trauma and violence. https://www.samhsa.gov/trauma-violence.
774 Substance Abuse and Mental Health Services Administration. (2022). Trauma and violence. https://www.samhsa.gov/trauma-violence.
775 Lortye, S. A., Will, J. P., Marquenie, L. A., Goudriaan, A. E., Arntz, A., & de Waal, M. M. (2021). Treating posttraumatic stress disorder in substance use disorder patients with co-occurring posttraumatic stress disorder: Study protocol for a randomized controlled trial to compare the effectiveness of different types and timings of treatment. BMC Psychiatry, 21(1), 442.34493253
776 Lortye, S. A., Will, J. P., Marquenie, L. A., Goudriaan, A. E., Arntz, A., & de Waal, M. M. (2021). Treating posttraumatic stress disorder in substance use disorder patients with co-occurring posttraumatic stress disorder: Study protocol for a randomized controlled trial to compare the effectiveness of different types and timings of treatment. BMC Psychiatry, 21(1), 442.34493253
777 Substance Abuse and Mental Health Services Administration. (2020). Substance use treatment for persons with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. SAMHSA Publication No. PEP20-02-01-004. Substance Abuse and Mental Health Services Administration.
778 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
779 Hopper, E. K., Bassuk, E. L., & Olivet, J. (2010). Shelter from the storm: Trauma-informed care in homelessness services settings. Open Health Services and Policy Journal, 3, 80–100.
780 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
781 Substance Abuse and Mental Health Services Administration. (2020). Substance use treatment for persons with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. SAMHSA Publication No. PEP20-02-01-004. Substance Abuse and Mental Health Services Administration.
782 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
783 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
784 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
785 Substance Abuse and Mental Health Services Administration. (2020). Substance use treatment for persons with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. SAMHSA Publication No. PEP20-02-01-004. Substance Abuse and Mental Health Services Administration.
786 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. HHS Publication No. (SMA) 14-4884. Substance Abuse and Mental Health Services Administration.
787 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
788 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. HHS Publication No. (SMA) 14-4884. Substance Abuse and Mental Health Services Administration.
789 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
790 Ginwright, S. (2018). The future of healing: Shifting from trauma informed care to healing centered engagement. https://ginwright.medium.com/the-future-of-healing-shifting-from-trauma-informed-care-to-healing-centered-engagement-634f557ce69c.
791 Ginwright, S. (2018). The future of healing: Shifting from trauma informed care to healing centered engagement. https://ginwright.medium.com/the-future-of-healing-shifting-from-trauma-informed-care-to-healing-centered-engagement-634f557ce69c.
792 Ginwright, S. (2018). The future of healing: Shifting from trauma informed care to healing centered engagement. https://ginwright.medium.com/the-future-of-healing-shifting-from-trauma-informed-care-to-healing-centered-engagement-634f557ce69c.
793 Substance Abuse and Mental Health Services Administration. (2014). SAMHSA's concept of trauma and guidance for a trauma-informed approach. HHS Publication No. (SMA) 14-4884. Substance Abuse and Mental Health Services Administration.
794 Schaal, S., Koebach, A., Hinkel, H., & Elbert, T. (2015). Posttraumatic stress disorder according to DSM-5 and DSM-IV diagnostic criteria: A comparison in a sample of Congolese ex-combatants. European Journal of Psychotraumatology, 6, 24981.25720994
795 Schaal, S., Koebach, A., Hinkel, H., & Elbert, T. (2015). Posttraumatic stress disorder according to DSM-5 and DSM-IV diagnostic criteria: A comparison in a sample of Congolese ex-combatants. European Journal of Psychotraumatology, 6, 24981.25720994
796 Hecker, T., Hermenau, K., Crombach, A., & Elbert, T. (2015). Treating traumatized offenders and veterans by means of narrative exposure therapy. Frontiers in Psychiatry, 6, 80.26157395
797 Pietrzak, R. H., Goldstein, R. B., Southwick, S. M., & Grant, B. F. (2011). Prevalence and Axis I comorbidity of full and partial posttraumatic stress disorder in the United States: Results from wave 2 of the National Epidemiologic Survey on Alcohol and Related Condition. Journal of Anxiety Disorders, 25(3), 456–465.21168991
798 U.S. Department of Veterans Affairs. (2022). Trauma, PTSD and treatment. https://www.ptsd.va.gov/professional/treat/cooccurring/index.asp.
799 Substance Abuse and Mental Health Services Administration. (2018). National Strategy for Trauma-Informed Care Operating Plan. https://www.samhsa.gov/sites/default/fíles/trauma-informed-care-operating-plan.pdf.
800 Ross, S. L., Sharma-Patel, K., Brown, E. J., Huntt, J. S., & Chaplin, W. F. (2021). Complex trauma and trauma-focused cognitive-behavioral therapy: How do trauma chronicity and PTSD presentation affect treatment outcome?. Child Abuse & Neglect, 111, 104734.33162104
801 Centers for Disease Control and Prevention. (2019). Adverse childhood experiences (ACEs). Preventing early trauma to improve adult health. CDC Vitalsigns. https://www.cdc.gov/vitalsigns/aces/pdf/vs-1105-aces-H.pdf.
802 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
803 Centers for Disease Control and Prevention. (2019). Adverse childhood experiences (ACEs). Preventing early trauma to improve adult health. CDC Vitalsigns. https://www.cdc.gov/vitalsigns/aces/pdf/vs-1105-aces-H.pdf.
804 Cicchetti, D., & Handley, E. D. (2019). Child maltreatment and the development of substance use and disorder. Neurobiology of Stress, 10, 100144.30937350
805 Chandler, G. E., Kalmakis, K. A., & Murtha, T. (2018). Screening adults with substance use disorder for adverse childhood experiences. Journal of Addictions Nursing, 29(3), 172–178.30180003
806 Parisi, A., Jordan, B., Jensen, T., & Howard, M. O. (2022). The impact of sexual victimization on substance use disorder treatment completion: A systematic review and meta-analysis. Substance Abuse, 43(1), 131–142.32432522
807 Han, B. H., Doran, K. M., & Krawczyk, N. (2022). National trends in substance use treatment admissions for opioid use disorder among adults experiencing homelessness. Journal of Substance Abuse Treatment, 132, 108504.34102461
808 McGinty, E. E., & Webster, D. W. (2017). The roles of alcohol and drugs in firearm violence. JAMA Internal Medicine, 177(3), 324–325.28055044
809 Hill, A. L., Miller, E., Borrero, S., Zelazny, S., Miller-Walfish, S., Talis, J., … Chang, J. C. (2021). Family planning providers' assessment of intimate partner violence and substance use. Journal of Women's Health (2002), 30(9), 1225–1232.
810 Magwood, O., Salvalaggio, G., Beder, M., Kendall, C., Kpade, V., Daghmach, W., … Pottie, K. (2020). The effectiveness of substance use interventions for homeless and vulnerably housed persons: A systematic review of systematic reviews on supervised consumption facilities, managed alcohol programs, and pharmacological agents for opioid use disorder. PLoS One, 15(1), e0227298.31945092
811 Chaudhri, S., Zweig, K. C., Hebbar, P., Angell, S., & Vasan, A. (2019). Trauma-informed care: A strategy to improve primary healthcare engagement for persons with criminal justice system involvement. Journal of General Internal Medicine, 34(6), 1048–1052.30912031
812 Vest, B. M., Hoopsick, R. A., Homish, D. L., Daws, R. C., & Homish, G. G. (2018). Childhood trauma, combat trauma, and substance use in National Guard and reserve soldiers. Substance Abuse, 39(4), 452–460.29485365
813 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
814 Back, S. E., Killeen, T., Badour, C. L., Flanagan, J. C., Allan, N. P., Ana, E. S., Lozano, B., Korte, K. J., Foa, E. B., & Brady, K. T (2019). Concurrent treatment of substance use disorders and PTSD using prolonged exposure: A randomized clinical trial in military veterans. Addictive Behaviors, 90, 369–377.30529244
815 Back, S. E., Killeen, T., Badour, C. L., Flanagan, J. C., Allan, N. P., Ana, E. S., Lozano, B., Korte, K. J., Foa, E. B., & Brady, K. T (2019). Concurrent treatment of substance use disorders and PTSD using prolonged exposure: A randomized clinical trial in military veterans. Addictive Behaviors, 90, 369–377.30529244
816 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
817 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
818 Substance Abuse and Mental Health Services Administration. (2015). Trauma-informed care in behavioral health services: Quick guide for clinicians. SAMHSA Publication No. (SMA) 15-4912. Substance Abuse and Mental Health Services Administration.
819 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 14-4816. Substance Abuse and Mental Health Services Administration.
820 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
821 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
822 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
823 Waits, W., Marumoto, M., & Weaver, J. (2017). Accelerated resolution therapy (ART): A review and research to date. Current Psychiatry Reports, 19(3), 1–7.28091799
824 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
825 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
826 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
827 American Psychological Association. (n.d.). Dialectical behavior therapy. https://dictionary.apa.org/dialectical-behavior-therapy.
828 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
829 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
830 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
831 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
832 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
833 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
834 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
835 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
836 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
837 Miller, W. R., & Rollnick, S. (2002). Motivational interviewing: Preparing people for change (2nd ed.). Guilford Press.
838 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
839 Arkowitz, H., Miller, W. R., & Rollnick, S. (2015). Motivational interviewing in the treatment of psychological problems (2nd ed.). Guilford Press.
840 Shulman, M., Pruzan, K., & Carpenter, K. M. (2021). Motivational enhancement. In K. T. Brady, F. R. Levin, M. Galantar, & H. D. Kleber (Eds.), The American Psychiatric Association Publishing textbook of substance use disorder treatment (6th ed., pp. 379–394). American Psychiatric Association Publishing.
841 Shulman, M., Pruzan, K., & Carpenter, K. M. (2021). Motivational enhancement. In K. T. Brady, F. R. Levin, M. Galantar, & H. D. Kleber (Eds.), The American Psychiatric Association Publishing textbook of substance use disorder treatment (6th ed., pp. 379–394). American Psychiatric Association Publishing.
842 Shulman, M., Pruzan, K., & Carpenter, K. M. (2021). Motivational enhancement. In K. T. Brady, F. R. Levin, M. Galantar, & H. D. Kleber (Eds.), The American Psychiatric Association Publishing textbook of substance use disorder treatment (6th ed., pp. 379–394). American Psychiatric Association Publishing.
843 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
844 Miller, W. R., & Sanchez, V. C. (1994). Motivating young adults for treatment and lifestyle change. In G. Howard & P. Nathan (Eds.), Alcohol use and misuse by young adults (pp. 55–82). University of Notre Dame Press.
845 Norcross, J. C., Krebs, P. M., & Prochaska, J. O. (2011). Stages of change. Journal of Clinical Psychology, 67(2), 143–154.21157930
846 Forman, D. P., & Moyers, T. B. (2019). With odds of a single session, motivational interviewing is a good bet. Psychotherapy (Chicago, Ill.), 56(1), 62–66.30667246
847 Miller, W. R., & Rollnick, S. (2013). Motivational interviewing: Helping people change (3rd ed.). Guilford Press.
848 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
849 Hogue, A., Henderson, C. E., Becker, S. J., & Knight, D. K. (2018). Evidence base on outpatient behavioral treatments for adolescent substance use, 2014-2017: Outcomes, treatment delivery, and promising horizons. Journal of Clinical Child and Adolescent Psychology, 47(4), 499–526.29893607
850 Santa Ana, E. J., LaRowe, S. D., Gebregziabher, M., Morgan-Lopez, A. A., Lamb, K., Beavis, K. A., … Martino, S. (2021). Randomized controlled trial of group motivational interviewing for veterans with substance use disorders. Drug and Alcohol Dependence, 223, 108716.33873028
851 Perry, A. E., Martyn-St. James, M., Burns, L., Hewitt, C., Glanville, J. M., Aboaja, A., … Swami, S. (2019). Interventions for drug-using offenders with co-occurring mental health problems. Cochrane Database of Systematic Reviews. doi:10.1002/14651858.CD010901.pub3.
852 Polcin, D. L., Korcha, R., Witbrodt, J., Mericle, A. A., & Mahoney, E. (2018). Motivational interviewing case management (MICM) for persons on probation or parole entering sober living houses. Criminal Justice and Behavior, 45(11), 1634–1659.30559549
853 Madson, M., Schumacher, J., Baer, J., & Martino, S. (2016). Motivational interviewing for substance use: Mapping out the next generation of research. Journal of Substance Abuse Treatment, 65, 1–5.26971078
854 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
855 Santa Ana, E. J., LaRowe, S. D., Gebregziabher, M., Morgan-Lopez, A. A., Lamb, K., Beavis, K. A., … Martino, S. (2021). Randomized controlled trial of group motivational interviewing for veterans with substance use disorders. Drug and Alcohol Dependence, 223, 108716.33873028
856 Madson, M., Schumacher, J., Baer, J., & Martino, S. (2016). Motivational interviewing for substance use: Mapping out the next generation of research. Journal of Substance Abuse Treatment, 65, 1–5.26971078
857 DiClemente, C. C., Corno, C. M., Graydon, M. M., Wiprovnick, A. E., & Knoblach, D. J. (2017). Motivational interviewing, enhancement, and brief interventions over the last decade: A review of reviews of efficacy and effectiveness. Psychology of Addictive Behaviors, 31(8), 862–887.29199843
858 Sayegh, C. S., Huey, S. J., Jr., Zara, E. J., & Jhaveri, K. (2017). Follow-up treatment effects of contingency management and motivational interviewing on substance use: A meta-analysis. Psychology of Addictive Behaviors, 31(4), 403–414.28437121
859 Santa Ana, E. J., LaRowe, S. D., Gebregziabher, M., Morgan-Lopez, A. A., Lamb, K., Beavis, K. A., … Martino, S. (2021). Randomized controlled trial of group motivational interviewing for veterans with substance use disorders. Drug and Alcohol Dependence, 223, 108716.33873028
860 Copeland, J., Gates, P., & Pokorski, I. (2017). A narrative review of psychological cannabis use treatments with and without pharmaceutical adjunct. Current Pharmaceutical Design, 22(42), 6397–6408.
861 Naar, S., & Safren, S. A. (2017). Motivational interviewing and CBT: Combining strategies for maximum effectiveness. Guilford Press.
862 Sayegh, C. S., Huey, S. J., Jr., Zara, E. J., & Jhaveri, K. (2017). Follow-up treatment effects of contingency management and motivational interviewing on substance use: A meta-analysis. Psychology of Addictive Behaviors, 31(4), 403–414.28437121
863 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
864 Hogue, A., Schumm, J. A., MacLean, A., & Bobek, M. (2022). Couple and family therapy for substance use disorders: Evidence-based update 2010-2019. Journal of Marital and Family Therapy, 48(1), 178–203.34435387
865 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
866 Substance Abuse and Mental Health Services Administration. (2014). Trauma-informed care in behavioral health services. Treatment Improvement Protocol (TIP) Series 57. HHS Publication No. (SMA) 13-4816. Substance Abuse and Mental Health Services Administration.
867 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
868 Black, C. (2018). Unspoken legacy: Addressing the impact of trauma and addiction within the family. Central Recovery Press.
869 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
870 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
871 Black, C. (2018). Unspoken legacy: Addressing the impact of trauma and addiction within the family. Central Recovery Press.
872 Hogue, A., Schumm, J. A., MacLean, A., & Bobek, M. (2022). Couple and family therapy for substance use disorders: Evidence-based update 2010-2019. Journal of Marital and Family Therapy, 48(1), 178–203.34435387
873 Haverfield, M. C., & Theiss, J. A. (2016). Parent's alcoholism severity and family topic avoidance about alcohol as predictors of perceived stigma among adult children of alcoholics: Implications for emotional and psychological resilience. Health Communication, 31(5), 606–616.26452454
874 Haverfield, M. C., & Theiss, J. A. (2016). Parent's alcoholism severity and family topic avoidance about alcohol as predictors of perceived stigma among adult children of alcoholics: Implications for emotional and psychological resilience. Health Communication, 31(5), 606–616.26452454
875 Smith, V. C., Wilson, C. R., & Committee on Substance Use and Prevention. (2016). Families affected by parental substance use. Pediatrics, 138(2), e20161575.
876 Haverfield, M. C., & Theiss, J. A. (2016). Parent's alcoholism severity and family topic avoidance about alcohol as predictors of perceived stigma among adult children of alcoholics: Implications for emotional and psychological resilience. Health Communication, 31(5), 606–616.26452454
877 Lander, L., Howsare, J., & Byrne, M. (2013). The impact of substance use disorders on families and children: From theory to practice. Social Work in Public Health, 28(3-4), 194–205.23731414
878 McCrady, B. S., & Flanagan, J. C. (2021). The role of the family in alcohol use disorder recovery for adults. Alcohol Research: Current Reviews, 41(1), 06.33981521
879 Lander, L., Howsare, J., & Byrne, M. (2013). The impact of substance use disorders on families and children: From theory to practice. Social Work in Public Health, 28(3-4), 194–205.23731414
880 McCrady, B. S., & Flanagan, J. C. (2021). The role of the family in alcohol use disorder recovery for adults. Alcohol Research: Current Reviews, 41(1), 06.33981521
881 McCrady, B. S., & Flanagan, J. C. (2021). The role of the family in alcohol use disorder recovery for adults. Alcohol Research: Current Reviews, 41(1), 06.33981521
882 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
883 Smith, J. C., Alderman, L., Attell, B. K., Avila Rodriguez, W., Covington, J., Manteuffel, B., … Minyard, K. (2021). Dynamics of parental opioid use and children's health and well-being: An integrative systems mapping approach. Frontiers in Psychology, 12, 687641.34267711
884 Smith, J. C., Alderman, L., Attell, B. K., Avila Rodriguez, W., Covington, J., Manteuffel, B., … Minyard, K. (2021). Dynamics of parental opioid use and children's health and well-being: An integrative systems mapping approach. Frontiers in Psychology, 12, 687641.34267711
885 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
886 Smith, J. C., Alderman, L., Attell, B. K., Avila Rodriguez, W., Covington, J., Manteuffel, B., … Minyard, K. (2021). Dynamics of parental opioid use and children's health and well-being: An integrative systems mapping approach. Frontiers in Psychology, 12, 687641.34267711
887 Smith, J. C., Alderman, L., Attell, B. K., Avila Rodriguez, W., Covington, J., Manteuffel, B., … Minyard, K. (2021). Dynamics of parental opioid use and children's health and well-being: An integrative systems mapping approach. Frontiers in Psychology, 12, 687641.34267711
888 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
889 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
890 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
891 Smith, J. C., Alderman, L., Attell, B. K., Avila Rodriguez, W., Covington, J., Manteuffel, B., … Minyard, K. (2021). Dynamics of parental opioid use and children's health and well-being: An integrative systems mapping approach. Frontiers in Psychology, 12, 687641.34267711
892 Lander, L., Howsare, J., & Byrne, M. (2013). The impact of substance use disorders on families and children: From theory to practice. Social Work in Public Health, 28(3-4), 194–205.23731414
893 Klostermann, K., & O'Farrell, T. J. (2021). Couple and family therapy in treatment of alcoholism and drug abuse. In N. el-Guebaly, G. Carrà, M. Galanter, & A. M. Baldacchino (Eds.), Textbook of addiction treatment (3rd ed.) (pp. 447–458). Springer.
894 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
895 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
896 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
897 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
898 Liddle, H. A., Dakof, G. A., Rowe, C. L., Henderson, C., Greenbaum, P., Wang, W., & Alberga, L. (2018). Multidimensional family therapy as a community-based alternative to residential treatment for adolescents with substance use and co-occurring mental health disorders. Journal of Substance Abuse Treatment, 90, 47–56.29866383
899 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
900 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
901 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
902 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
903 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
904 Meyers, R. J., Roozen, H. G., & Smith, J. E. (2011). The community reinforcement approach: An update of the evidence. Alcohol Research & Health, 33(4), 380–388.23580022
905 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
906 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
907 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
908 Helium, R., Bilberg, R., Bischof, G., & Nielsen, A. S. (2021). How concerned significant others experience Community Reinforcement and Family Training (CRAFT) — A qualitative study. BMC Family Practice, 22(1), 241.34861827
909 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
910 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment and family therapy. Treatment Improvement Protocol (TIP) Series 39. SAMHSA Publication No. PEP20-02-02-012. Substance Abuse and Mental Health Services Administration.
911 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
912 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
913 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
914 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
915 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
916 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
917 Ariss, T., & Fairbairn, C. E. (2020). The effect of significant other involvement in treatment for substance use disorders: A metaanalysis. Journal of Consulting and Clinical Psychology, 88(6), 526–540.32162930
918 Substance Abuse and Mental Health Services Administration. (2021). National Survey of Substance Abuse Treatment Services (N-SSATS): 2020. Data on substance abuse treatment facilities. Substance Abuse and Mental Health Services Administration.
919 U.S. Department of Health & Human Services. (2016). Facing addiction in America: The Surgeon General's report on alcohol, drugs, and health.
920 Carroll, K. M., & Kiluk, B. D. (2017). Cognitive behavioral interventions for alcohol and drug use disorders: Through the stage model and back again. Psychology of Addictive Behaviors, 31(8), 847–861.28857574
921 Kiluk, B. D. (2019). Computerized cognitive behavioral therapy for substance use disorders: A summary of the evidence and potential mechanisms of behavior change. Perspectives on Behavior Science, 42(3), 465–478.31976445
922 Morin, J. F. G., Harris, M., & Conrod, P. J. (2017). A review of CBT treatments for substance use disorders. Oxford Handbooks Online. https://www.oxfordhandbooks.com/view/10.1093/oxfordhb/9780199935291.001.0001/oxfordhb-9780199935291-e-57.
923 American Society of Addiction Medicine. (n.d.). The ASAM Criteria^®^ Assessment Interview Guide. https://www.asam.org/asam-criteria/criteria-intake-assessment-form.
924 Scherer, K. R. (2005). Unconscious Processes in Emotion: The Bulk of the Iceberg. In L. F. Barrett, P. M. Niedenthal, & P. Winkielman (Eds.), Emotion and consciousness (pp. 312–334). The Guilford Press.
925 Sivec, H. J., & Montesano, V. L. (2013). Clinical process examples of cognitive behavioral therapy for psychosis. Psychotherapy, 50(3), 458–463.24000871
926 Morin, J. F. G., Harris, M., & Conrod, P. J. (2017). A review of CBT treatments for substance use disorders. Oxford Handbooks Online. https://www.oxfordhandbooks.com/view/10.1093/oxfordhb/9780199935291.001.0001/oxfordhb-9780199935291-e-57.
927 Substance Abuse and Mental Health Services Administration. (2019) Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
928 Marlatt, G. A., & Donovan, D. M. (Eds.). (2005). Relapse prevention: Maintenance strategies in the treatment of addictive behaviors (2nd ed.). Guilford Press.
929 Marlatt, G. A., Parks, G. A., & Witkiewitz, K. (2002). Clinical guidelines for implementing relapse prevention therapy: A guideline developed for behavioral health recovery management project. University of Washington.
930 National Institute on Drug Abuse. (1998). A cognitive behavioral approach: treating cocaine addiction. Therapy manuals for drug addiction, Manual Number 1. National Institutes of Health Publication Number 98-4308. U.S. Department of Health and Human Services.
931 Ray, L. A., Meredith, L. R., Kiluk, B. D., Walthers, J., Carroll, K. M., & Magill, M. (2020). Combined pharmacotherapy and cognitive behavioral therapy for adults with alcohol or substance use disorders: A systematic review and meta-analysis. JAMA Network Open, 3(6), e208279–e208279.32558914
932 Magill, M., Ray, L., Kiluk, B., Hoadley, A., Bernstein, M., Tonigan, J. S., & Carroll, K. (2019). A meta-analysis of cognitive-behavioral therapy for alcohol or other drug use disorders: Treatment efficacy by contrast condition. Journal of Consulting and Clinical Psychology, 87(12), 1093.31599606
933 Ray, L. A., Meredith, L. R., Kiluk, B. D., Walthers, J., Carroll, K. M., & Magill, M. (2020). Combined pharmacotherapy and cognitive behavioral therapy for adults with alcohol or substance use disorders: A systematic review and meta-analysis. JAMA Network Open, 3(6), e208279–e208279.32558914
934 Ray, L. A., Meredith, L. R., Kiluk, B. D., Walthers, J., Carroll, K. M., & Magill, M. (2020). Combined pharmacotherapy and cognitive behavioral therapy for adults with alcohol or substance use disorders: A systematic review and meta-analysis. JAMA Network Open, 3(6), e208279–e208279.32558914
935 Magill, M., Ray, L., Kiluk, B., Hoadley, A., Bernstein, M., Tonigan, J. S., & Carroll, K. (2019). A meta-analysis of cognitive-behavioral therapy for alcohol or other drug use disorders: Treatment efficacy by contrast condition. Journal of Consulting and Clinical Psychology, 87(12), 1093.31599606
936 Carroll, K. M., & Kiluk, B. D. (2017). Cognitive behavioral interventions for alcohol and drug use disorders: Through the stage model and back again. Psychology of Addictive Behaviors, 31(8), 847–861.28857574
937 Carroll, K. M., & Kiluk, B. D. (2017). Cognitive behavioral interventions for alcohol and drug use disorders: Through the stage model and back again. Psychology of Addictive Behaviors, 31(8), 847–861.28857574
938 Carroll, K. M., & Kiluk, B. D. (2017). Cognitive behavioral interventions for alcohol and drug use disorders: Through the stage model and back again. Psychology of Addictive Behaviors, 31(8), 847–861.28857574
939 Kiluk, B. D. (2019). Computerized cognitive behavioral therapy for substance use disorders: A summary of the evidence and potential mechanisms of behavior change. Perspectives on Behavior Science, 42(3), 465–478.31976445
940 Petry, N. M., Alessi, S. M., Olmstead, T. A., Rash, C. J., & Zajac, K. (2017). Contingency management treatment for substance use disorders: How far has it come, and where does it need to go? Psychology of Addictive Behaviors, 31(8), 897–906.28639812
941 National Institute on Drug Abuse. (2018). Contingency management interventions/motivational incentives (alcohol, stimulants, opioids, marijuana, nicotine). In Principles of drug addiction treatment: A research-based guide (3rd ed.). https://nida.nih.gov/publications/principles-drug-addiction-treatment-research-based-guide-third-edition/preface.
942 Regier, P. S., & Redish, A. D. (2015). Contingency management and deliberative decision-making processes. Frontiers in Psychiatry, 6, 76.26082725
943 AshaRani, P. V., Hombali, A., Seow, E., Ong, W. J., Tan, J. H., & Subramaniam, M. (2020). Non-pharmacological interventions for methamphetamine use disorder: A systematic review. Drug and Alcohol Dependence, 212, 108060.32445927
944 Brown, H. D., & DeFulio, A. (2020). Contingency management for the treatment of methamphetamine use disorder: A systematic review. Drug and Alcohol Dependence, 216, 108307.33007699
945 Bolívar, H. A., Klemperer, E. M., Coleman, S. R., DeSarno, M., Skelly, J. M., & Higgins, S. T. (2021). Contingency management for patients receiving medication for opioid use disorder: A systematic review and meta-analysis. JAMA Psychiatry, 78(10), 1092–1102.34347030
946 Winters, K. C., Mader, J., Budney, A. J., Stanger, C., Knapp, A. A., & Walker, D. D. (2021). Interventions for cannabis use disorder. Current Opinion in Psychology, 38, 67–74.33338844
947 Dallery, J., Raiff, B. R., Kim, S. J., Marsch, L. A., Stitzer, M., & Grabinski, M. J. (2017). Nationwide access to an internetlUbased contingency management intervention to promote smoking cessation: A randomized controlled trial. Addiction, 112(5), 875–883.27923264
948 Brown, H. D., & DeFulio, A. (2020). Contingency management for the treatment of methamphetamine use disorder: A systematic review. Drug and Alcohol Dependence, 216, 108307.33007699
949 AshaRani, P. V., Hombali, A., Seow, E., Ong, W. J., Tan, J. H., & Subramaniam, M. (2020). Non-pharmacological interventions for methamphetamine use disorder: A systematic review. Drug and Alcohol Dependence, 212, 108060.32445927
950 Bolívar, H. A., Klemperer, E. M., Coleman, S. R., DeSarno, M., Skelly, J. M., & Higgins, S. T. (2021). Contingency management for patients receiving medication for opioid use disorder: A systematic review and meta-analysis. JAMA Psychiatry, 78(10), 1092–1102.34347030
951 De Crescenzo, F., Ciabattini, M., D'Alò, G. L., De Giorgi, R., Del Giovane, C., Cassar, C., … Cipriani, A. (2018). Comparative efficacy and acceptability of psychosocial interventions for individuals with cocaine and amphetamine addiction: A systematic review and network meta-analysis. PLoS Medicine, 15(12), e1002715.30586362
952 Ginley, M. K., Pfund, R. A., Rash, C. J., & Zajac, K. (2021). Long-term efficacy of contingency management treatment based on objective indicators of abstinence from illicit substance use up to 1 year following treatment: A metaanalysis. Journal of Consulting and Clinical Psychology, 89(1), 58–71.33507776
953 Ginley, M. K., Pfund, R. A., Rash, C. J., & Zajac, K. (2021). Long-term efficacy of contingency management treatment based on objective indicators of abstinence from illicit substance use up to 1 year following treatment: A metaanalysis. Journal of Consulting and Clinical Psychology, 89(1), 58–71.33507776
954 Pfund, R. A., Cook, J. E., McAfee, N. W., Huskinson, S. L., & Parker, J. D. (2021). Challenges to conducting contingency management treatment for substance use disorders: Practice recommendations for clinicians. Professional Psychology, Research and Practice, 52(2), 137–145.34421192
955 Pfund, R. A., Cook, J. E., McAfee, N. W., Huskinson, S. L., & Parker, J. D. (2021). Challenges to conducting contingency management treatment for substance use disorders: Practice recommendations for clinicians. Professional Psychology, Research and Practice, 52(2), 137–145.34421192
956 Dallery, J., Defulio, A., & Raiff, B. R. (2023). Digital contingency management in the treatment of substance use disorders. Policy Insights from the Behavioral and Brain Sciences, 10(1), 51–58.
957 Dallery, J., Defulio, A., & Raiff, B. R. (2023). Digital contingency management in the treatment of substance use disorders. Policy Insights from the Behavioral and Brain Sciences, 10(1), 51–58.
958 Dallery, J., Defulio, A., & Raiff, B. R. (2023). Digital contingency management in the treatment of substance use disorders. Policy Insights from the Behavioral and Brain Sciences, 10(1), 51–58.
959 Coughlin, L. N., Salino, S., Jennings, C., Lacek, M., Townsend, W., Koffarnus, M. N., & Bonar, E. E. (2023). A systematic review of remotely delivered contingency management treatment for substance use. Journal of Substance Use and Addiction Treatment, 147, 208977.36804352
960 Getty, C. A., Morande, A., Lynskey, M., Weaver, T., & Metrebian, N. (2019). Mobile telephone-delivered contingency management interventions promoting behaviour change in individuals with substance use disorders: A meta-analysis. Addiction (Abingdon, England), 114(11), 1915–1925.31265747
961 Coughlin, L. N., Salino, S., Jennings, C., Lacek, M., Townsend, W., Koffarnus, M. N., & Bonar, E. E. (2023). A systematic review of remotely delivered contingency management treatment for substance use. Journal of Substance Use and Addiction Treatment, 147, 208977.36804352
962 Getty, C. A., Morande, A., Lynskey, M., Weaver, T., & Metrebian, N. (2019). Mobile telephone-delivered contingency management interventions promoting behaviour change in individuals with substance use disorders: A meta-analysis. Addiction (Abingdon, England), 114(11), 1915–1925.31265747
963 Hammond, A. S., Sweeney, M. M., Chikosi, T. U., & Stitzer, M. L. (2021). Digital delivery of a contingency management intervention for substance use disorder: A feasibility study with DynamiCare Health. Journal of Substance Abuse Treatment, 126, 108425.34116816
964 Recovery Research Institute. (n.d.). Technology-enhanced contingency management: Exploring the feasibility. https://www.recoveryanswers.org/research-post/contingency-management-app-exploring-feasibility-automated-digital-contingency-management-substance-use-disorder/.
965 Koob, G. F., & Volkow, N. D. (2016). Neurobiology of addiction: A neurocircuitry analysis. Lancet Psychiatry, 3(8), 760–773.27475769
966 Milivojevic, V., & Sinha, R. (2018). Central and peripheral markers of stress response for addiction risk and relapse vulnerability. Trends in Molecular Medicine, 24(2), 173–186.29396148
967 Milivojevic, V., & Sinha, R. (2018). Central and peripheral markers of stress response for addiction risk and relapse vulnerability. Trends in Molecular Medicine, 24(2), 173–186.29396148
968 Koob, G. F., & Volkow, N. D. (2016). Neurobiology of addiction: A neurocircuitry analysis. Lancet Psychiatry, 3(8), 760–773.27475769
969 Psychology Today. (2022). Mindfulness. Sussex. https://www.psychologytoday.com/us/basics/mindfulness.
970 Witkiewitz, K., Greenfield, B. L., & Bowen, S. (2013). Mindfulness-based relapse prevention with racial and ethnic minority women. Addictive Behaviors, 38(12), 2821–2824.24018224
971 Greenfield, B. L., Roos, C., Hagler, K. J., Stein, E., Bowen, S., & Witkiewitz, K. A. (2018). Race/ethnicity and racial group composition moderate the effectiveness of mindfulness-based relapse prevention for substance use disorder. Addictive Behaviors, 81, 96–103.29454179
972 Korecki, J. R., Schwebel, F. J., Votaw, V. R., & Witkiewitz, K. (2020). Mindfulness-based programs for substance use disorders: A systematic review of manualized treatments. Substance Abuse Treatment, Prevention, and Policy, 15(1), 51.
973 Marlatt, G. A., Dillworth, T. M., Bowen, S. W., Parks, G. A., & MacPherson, L. M. (2004). Vipassana meditation as a treatment for alcohol and drug use disorders. In S. C. Hayes, V. M. Follette, & M. M. Linehan (Eds.), Mindfulness and acceptance: Expanding the cognitive-behavioral tradition (pp. 261–287). Guilford Press.
974 Priddy, S. E., Howard, M. O., Hanley, A. W., Riquino, M. R., Friberg-Felsted, K., & Garland, E. L. (2018). Mindfulness meditation in the treatment of substance use disorders and preventing future relapse: Neurocognitive mechanism and clinical implications. Substance Abuse and Rehabilitation, 9, 103–114.30532612
975 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
976 Priddy, S. E., Howard, M. O., Hanley, A. W., Riquino, M. R., Friberg-Felsted, K., & Garland, E. L. (2018). Mindfulness meditation in the treatment of substance use disorders and preventing future relapse: Neurocognitive mechanism and clinical implications. Substance Abuse and Rehabilitation, 9, 103–114.30532612
977 Garland, E. L. (2007). The meaning of mindfulness: A second-order cybernetics of stress, metacognition, and coping. Complementary Health Practice Review, 12(1), 15–30.
978 Lutz, A., Slagter, H. A., Dunne, J. D., Davidson, R. J. (2008). Attention regulation and monitoring in meditation. Trends in Cognitive Science, 12(4), 163–169.
979 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
980 Kabat-Zinn, J., Lipworth L., & Burney, R. (1985). The clinical use of mindfulness meditation for the self-regulation of chronic pain. Journal of Behavioral Health Medicine, 8(2), 163–190.
981 Kabat-Zinn, J., Lipworth, L., Burney, R., Sellers, W., & Brew, M. (1984). Reproducibility and four year follow-up of a training program in mindfulness meditation for the self-regulation of chronic pain. Pain, 18, S303.
982 Korecki, J. R., Schwebel, F. J., Votaw, V. R., & Witkiewitz, K. (2020). Mindfulness-based programs for substance use disorders: A systematic review of manualized treatments. Substance Abuse Treatment, Prevention, and Policy, 15(1), 51.
983 Korecki, J. R., Schwebel, F. J., Votaw, V. R., & Witkiewitz, K. (2020). Mindfulness-based programs for substance use disorders: A systematic review of manualized treatments. Substance Abuse Treatment, Prevention, and Policy, 15(1), 51.
984 Garland, E. L., Baker, A. K., Riquino, M. R., & Priddy, S. E. (2019). Mindfulness-oriented recovery enhancement: A review of its theoretical underpinnings, clinical application, and biobehavioral mechanisms. In I. Ivtzan (Ed.), Handbook of mindfulness-based programmes: Mindfulness interventions from education to health and therapy (Ch. 26). Routledge.
985 Amaro, H., & Black, D. S. (2017). Moment-bymoment in women's recovery: Randomized controlled trial protocol to test the efficacy of a mindfulness-based intervention on treatment retention and relapse prevention among women in residential treatment for substance use disorder. Contemporary Clinical Trials, 62, 146–152.28918120
986 Korecki, J. R., Schwebel, F. J., Votaw, V. R., & Witkiewitz, K. (2020). Mindfulness-based programs for substance use disorders: A systematic review of manualized treatments. Substance Abuse Treatment, Prevention, and Policy, 15(1), 51.
987 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2^nd^ ed.). Guilford Press.
988 Korecki, J. R., Schwebel, F. J., Votaw, V. R., & Witkiewitz, K. (2020). Mindfulness-based programs for substance use disorders: A systematic review of manualized treatments. Substance Abuse Treatment, Prevention, and Policy, 15(1), 51.
989 Roos, C., Kirouac, M., Stein, E., Wilson, A., Bowen, S., & Witkiewitz, K. (2019). An open trial of rolling admission mindfulness-based relapse prevention (Rolling MBRP): Feasibility, acceptability, dose-response relations, and mechanism. Mindfulness (NY), 10(6), 1062–1073.
990 Roos, C., Kirouac, M., Stein, E., Wilson, A., Bowen, S., & Witkiewitz, K. (2019). An open trial of rolling admission mindfulness-based relapse prevention (Rolling MBRP): Feasibility, acceptability, dose-response relations, and mechanism. Mindfulness (NY), 10(6), 1062–1073.
991 Witkiewitz, K., Bowen, S., Harrop, E. N., Douglas, H., Enkema, M., & Sedgwick, C. (2014). Mindfulness-based treatment to prevent addictive behavior relapse: Theoretical models and hypothesized mechanisms of change. Substance Use & Misuse, 49(5), 513–524.24611847
992 Witkiewitz, K., Bowen, S., Harrop, E. N., Douglas, H., Enkema, M., & Sedgwick, C. (2014). Mindfulness-based treatment to prevent addictive behavior relapse: Theoretical models and hypothesized mechanisms of change. Substance Use & Misuse, 49(5), 513–524.24611847
993 Zhang, D., Lee, E. K. P., Mak, E. C. W., Ho, C. Y., & Wong, S. Y. S. (2021). Mindfulness-based interventions: An overall review. British Medical Bulletin, 138(1) 41–57.33884400
994 Ergas, O. (2015). The deeper teachings of mindfulness-based ‘interventions’ as a reconstruction of ‘education.’ Journal of Philosophy Education, 49(2), 203–220.
995 Witkiewitz, K., Bowen, S., Harrop, E. N., Douglas, H., Enkema, M., & Sedgwick, C. (2014). Mindfulness-based treatment to prevent addictive behavior relapse: Theoretical models and hypothesized mechanisms of change. Substance Use & Misuse, 49(5), 513–524.24611847
996 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
997 Harris, R. (n.d.). What is mindfulness? https://www.actmindfully.com.au/about-mindfulness/.
998 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
999 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
1000 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
1001 Project Air. (2018). A mindfulness activity you might like: Leaves on a stream. https://documents.uow.edu.au/content/groups/public/@web/@project-air/documents/doc/uow247535.pdf.
1002 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
1003 Bowen, S., Chawla, N., Grow, J., & Marlatt, G. A. (2021). Mindfulness-based relapse prevention for addictive behaviors: A clinician's guide (2nd ed.). Guilford Press.
1004 Zhang, D., Lee, E. K. P., Mak, E. C. W., Ho, C. Y., & Wong, S. Y. S. (2021). Mindfulness-based interventions: An overall review. British Medical Bulletin, 138(1) 41–57.33884400
1005 Sancho, M., De Gracia, M., Rodriguez, R. C., Mallorqui-Bague, N., Sanchez-Gonzalez, J., Trujols, J., … Menchon, J. M. (2018). Mindfulness-based interventions for the treatment of substance and behavioral addictions: A systematic review. Frontiers in Psychiatry, 9, 95.29651257
1006 Cavicchioli, M., Movalli, M., & Maffei, C. (2018). The clinical efficacy of mindfulness-based treatments for alcohol and drugs use disorders: A meta-analytic review of randomized and nonrandomized controlled trials. European Addiction Research, 24(3), 137–162.30016796
1007 Li, W., Howard, M. O., Garland, E. L., McGovern, P., & Lazar, M. (2017). Mindfulness treatment for substance misuse: A systematic review and meta-analysis. Journal of Substance Abuse Treatment, 75, 62–96.28153483
1008 Roos, C., Kirouac, M., Stein, E., Wilson, A., Bowen, S., & Witkiewitz, K. (2019). An open trial of rolling admission mindfulness-based relapse prevention (Rolling MBRP): Feasibility, acceptability, dose-response relations, and mechanism. Mindfulness (NY), 10(6), 1062–1073.
1009 Zhang, D., Lee, E. K. P., Mak, E. C. W., Ho, C. Y., & Wong, S. Y. S. (2021). Mindfulness-based interventions: An overall review. British Medical Bulletin, 138(1), 41–57.33884400
1010 Ergas, O. (2015). The deeper teachings of mindfulness-based ‘interventions’ as a reconstruction of ‘education.’ Journal of Philosophy Education, 49(2), 203–220.
1011 Witkiewitz, K., Greenfield, B. L., & Bowen, S. (2013). Mindfulness-based relapse prevention with racial and ethnic minority women. Addictive Behaviors, 38(12), 2821–2824.24018224
1012 Greenfield, B. L., Roos, C., Hagler, K. J., Stein, E., Bowen, S., & Witkiewitz, K. A. (2018). Race/ethnicity and racial group composition moderate the effectiveness of mindfulness-based relapse prevention for substance use disorder. Addictive Behaviors, 81, 96–103.29454179
1013 Osaji, J., Ojimba, C., & Ahmed, S. (2020). The use of acceptance and commitment therapy in substance use disorders: A review of literature. Journal of Clinical Medicine Research, 12(10), 629–633.33029268
1014 Mallik, D., Kaplan, J., Somohano, V., Bergman, A., & Bowen, S. (2021). Examining the role of craving, mindfulness, and psychological flexibility in a sample of individuals with substance use disorder. Substance Use & Misuse, 56(6), 782–786.33769196
1015 Shorey, R. C., Gawrysiak, M. J., Elmquist, J., Brem, M., Anderson, S., & Stuart, G. L. (2017). Experiential avoidance, distress tolerance, and substance use cravings among adults in residential treatment for substance use disorders. Journal of Addictive Diseases, 36(3), 151–157.28358236
1016 Lee, E. B., An, W., Levin, M. E., & Twohig, M. P. (2015). An initial meta-analysis of acceptance and commitment therapy for treating substance use disorders. Drug and Alcohol Dependence, 155, 1–7.26298552
1017 Dindo, L., Van Liew, J. R., & Arch, J. J. (2017). Acceptance and commitment therapy: A transdiagnostic behavioral intervention for mental health and mental conditions. Neurotherapeutics, 14(3), 546–553.28271287
1018 Substance Abuse and Mental Health Services Administration. (2021). Prevention and treatment of anxiety, depression, and suicidal thoughts and behaviors among college students. SAMHSA Publication No. PEP21-06-05-002. Substance Abuse and Mental Health Services Administration, National Mental Health and Substance Use Policy Laboratory.
1019 Kashdan, T. B., & Rottenberg, J. (2010). Psychological flexibility as a fundamental aspect of health. Clinical Psychology Review, 30(7), 865–878.21151705
1020 Levin, M. E., MacLane, C., Daflos, S., Seeley, J., Hayes, S. C., Biglan, A., & Pistorello, J. (2014). Examining psychological inflexibility as a transdiagnostic process across psychological disorders. Journal of Contextual Behavioral Science, 3(3), 155–163.29057212
1021 Dindo, L., Van Liew, J. R., & Arch, J. J. (2017). Acceptance and commitment therapy: A transdiagnostic behavioral intervention for mental health and medical conditions. Neurotherapeutics, 14(3), 546–553.28271287
1022 Dindo, L., Van Liew, J. R., & Arch, J. J. (2017). Acceptance and commitment therapy: a transdiagnostic behavioral intervention for mental health and medical conditions. Neurotherapeutics, 14(3), 546–553.28271287
1023 Polk, K., & Schoendorff, B. (2022). Moving toward what's important: An intro to the ACT Matrix. Praxis. https://www.praxiscet.com/posts/moving-toward-what-is-important-intro-act-matrix/.
1024 Gordon, T (2017). What is psychological flexibility? New Harbinger. https://www.newharbinger.com/blog/self-help/what-is-psychological-flexibility/.
1025 Krafft, J., Potts, S., Schoendorff, B., & Levin, M. E. (2019). A randomized controlled trial of multiple versions of an acceptance and commitment therapy matrix app for well-being. Behavior Modification, 43(2), 246–272.29262693
1026 Polk, K., & Schoendorff, B. (2022). Moving toward what's important: An intro to the ACT Matrix. Praxis. https://www.praxiscet.com/posts/moving-toward-what-is-important-intro-act-matrix/.
1027 Knight, S. (2022). How to use the ACT Matrix in the field of addiction: Values & the future self. https://www.youtube.com/watch?v=qX4iPQBH3Z0.
1028 Krafft, J., Potts, S., Schoendorff, B., & Levin, M. E. (2019). A randomized controlled trial of multiple versions of an acceptance and commitment therapy matrix app for well-being. Behavior Modification, 43(2), 246–272.29262693
1029 Dindo, L., Van Liew, J. R., & Arch, J. J. (2017). Acceptance and commitment therapy: A transdiagnostic behavioral intervention for mental health and mental conditions. Neurotherapeutics, 14(3), 546–553.28271287
1030 Feliu-Soler, A., Montesinos, F., Gutierrez-Martinez, O., Scott, W., McCracken, L. M., & Luciano, J. V. (2018). Current status of acceptance and commitment therapy for chronic pain: A narrative review. Journal of Pain Research, 11, 2145–2159.30323649
1031 Osaji, J., Ojimba, C., & Ahmed, S. (2020). The use of acceptance and commitment therapy in substance use disorders: A review of literature. Journal of Clinical Medicine Research, 12(10), 629–633.33029268
1032 Lee, E. B., An, W., Levin, M. E., & Twohig, M. P. (2015). An initial meta-analysis of acceptance and commitment therapy for treating substance use disorders. Drug and Alcohol Dependence, 155, 1–7.26298552
1033 Substance Abuse and Mental Health Services Administration. (2021). Prevention and treatment of anxiety, depression, and suicidal thoughts and behaviors among college students. SAMHSA Publication No. PEP21-06-05-002. Substance Abuse and Mental Health Services Administration, National Mental Health and Substance Use Policy Laboratory.
1034 Substance Abuse and Mental Health Services Administration. (2021). Prevention and treatment of anxiety, depression, and suicidal thoughts and behaviors among college students. SAMHSA Publication No. PEP21-06-05-002. Substance Abuse and Mental Health Services Administration, National Mental Health and Substance Use Policy Laboratory.
1035 Krafft, J., Potts, S., Schoendorff, B., & Levin, M. E. (2019). A randomized controlled trial of multiple versions of an acceptance and commitment therapy matrix app for well-being. Behavior Modification, 43(2), 246–272.29262693
1036 Lee, E. B., An, W., Levin, M. E., & Twohig, M. P. (2015). An initial meta-analysis of acceptance and commitment therapy for treating substance use disorders. Drug and Alcohol Dependence, 155, 1–7.26298552
1037 Krafft, J., Potts, S., Schoendorff, B., & Levin, M. E. (2019). A randomized controlled trial of multiple versions of an acceptance and commitment therapy matrix app for well-being. Behavior Modification, 43(2), 246–272.29262693
1038 Feliu-Soler, A., Montesinos, F., Gutierrez-Martinez, O., Scott, W., McCracken, L. M., & Luciano, J. V. (2018). Current status of acceptance and commitment therapy for chronic pain: A narrative review. Journal of Pain Research, 11, 2145–2159.30323649
1039 Kelly, J. F. (2017). Tens of millions successfully in long-term recovery—Let us find out how they did it. Addiction, 112(5), 762–763.28054421
1040 Bassuk, E. L., Hanson, J., Greene, R. N., Richard, M., & Laudet, A. (2016). Peer-delivered recovery support services for addictions in the United States: A systematic review. Journal of Substance Abuse Treatment, 63, 1–9.26882891
1041 Tracy, K., & Wallace, S. P. (2016). Benefits of peer support groups in the treatment of addiction. Substance Abuse and Rehabilitation, 7, 143–154.27729825
1042 Stanojlovic, M., & Davidson, L. (2021). Targeting the barriers in the substance use disorder continuum of care with peer recovery support. Substance Abuse: Research and Treatment, 15, 1178221820976988.34211275
1043 Gagne, C. A., Finch, W. L., Myrick, K. J., & Davis, L. M. (2018). Peer workers in the behavioral and integrated health workforce: Opportunities and future directions. American Journal of Preventive Medicine, 54(6), S258–S266.29779550
1044 Tracy, K., & Wallace, S. P. (2016). Benefits of peer support groups in the treatment of addiction. Substance Abuse and Rehabilitation, 7, 143–154.27729825
1045 Research Recovery Institute. (2023). 12-Step facilitation (TSF). https://www.recoveryanswers.org/resource/twelve-step-facilitation-tsf/.
1046 Kelly, J. F., Abry, A., Ferri, M., & Humphreys, K. (2020). Alcoholics Anonymous and 12-step facilitation treatments for alcohol use disorder: A distillation of a 2020 Cochrane Review for clinicians and policy makers. Alcohol and Alcoholism, 55(6), 641–651.32628263
1047 Kelly, J. F., Abry, A., Ferri, M., & Humphreys, K. (2020). Alcoholics Anonymous and 12-step facilitation treatments for alcohol use disorder: A distillation of a 2020 Cochrane review for clinicians and policy makers. Alcohol and Alcoholism, 55(6), 641–651.32628263
1048 Magill, M., Martino, S., & Wampold, B. (2021). The principles and practices of psychoeducation with alcohol or other drug use disorders: A review and brief guide. Journal of Substance Abuse Treatment, 126, 108442.34116812
1049 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1050 Magill, M., Martino, S., & Wampold, B. (2021). The principles and practices of psychoeducation with alcohol or other drug use disorders: A review and brief guide. Journal of Substance Abuse Treatment, 126, 108442.34116812
1051 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
1052 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
1053 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1054 Kargin, M., & Hicdurmaz, D. (2020). Psychoeducation program for substance use disorder: Effect on relapse rate, social functioning, perceived wellness, and coping. Journal of Psychosocial Nursing and Mental Health Services, 58(8), 39–47.
1055 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1056 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1057 National Institute on Drug Abuse. (2020). Drugs and the brain. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drugs-brain.
1058 National Institute on Drug Abuse. (2020). Drugs and the brain. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drugs-brain.
1059 National Institute on Drug Abuse. (2020). Drugs and the brain. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drugs-brain.
1060 National Institute on Drug Abuse. (2020). Drugs and the brain. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drugs-brain.
1061 National Institute on Drug Abuse. (2020). Drugs and the brain. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drugs-brain.
1062 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1063 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1064 Recovery Research Institute. (n.d.). The neuroscience of addiction recovery. https://www.recoveryanswers.org/recovery-101/brain-in-recovery/.
1065 Recovery Research Institute. (n.d.). The neuroscience of addiction recovery. https://www.recoveryanswers.org/recovery-101/brain-in-recovery/.
1066 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1067 National Institute on Drug Abuse. (2020). What is drug addiction? In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drug-misuse-addiction.
1068 National Institute on Drug Abuse. (2020). What is drug addiction? In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drug-misuse-addiction.
1069 Recovery Research Institute. (n.d.). Addiction 101: Definitions and terminology. https://www.recoveryanswers.org/addiction-101/definitions-terminology/.
1070 National Institute on Drug Abuse. (2020). Drugs and the brain. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drugs-brain.
1071 National Institute on Drug Abuse. (2020). What is drug addiction? In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drug-misuse-addiction.
1072 National Institute on Drug Abuse. (2020). What is drug addiction? In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/drug-misuse-addiction.
1073 Recovery Research Institute. (n.d.). Addiction: The risk factors. https://www.recoveryanswers.org/media/risk-factors-for-addiction-development/.
1074 Ekhtiari, H., Rezapour, T., Aupperle, R. L., & Paulus, M. P. (2017). Neuroscience-informed psychoeducation for addiction medicine: A neurocognitive perspective. Progress in Brain Research, 235, 239–264.29054291
1075 Substance Abuse and Mental Health Services Administration. (2022). Mental health and substance use disorders. https://www.samhsa.gov/find-help/disorders.
1076 National Institute on Drug Abuse. (2020). Preventing drug misuse and addiction: The best strategy. In Drugs, brains, and behavior: The science of addiction. https://nida.nih.gov/publications/drugs-brains-behavior-science-addiction/preventing-drug-misuse-addiction-best-strategy.
1077 Indian Health Service. (n.d.). Myths about substance use disorders. https://www.ihs.gov/asap/patients/myths/.
1078 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
1079 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
1080 National Harm Reduction Coalition. (2020). Principles of harm reduction. https://harmreduction.org/about-us/principles-of-harm-reduction/.
1081 Fentress, T., Wald, S., Brah, A., Leemon, G., Reyes, R., Alkhamees, F., … Collins, S. E. (2021). Dual study describing patient-driven harm reduction goal-setting among people experiencing homelessness and alcohol use disorder. Experimental and Clinical Psychopharmacology, 29(3), 261–271.34264737
1082 Huhn, A. S., & Gipson, C. D. (2021). Promoting harm reduction as a treatment outcome in substance use disorders. Experimental and Clinical Psychopharmacology, 29(3), 217–218.34264733
1083 National Institute on Drug Abuse. (2021). Words matter: Preferred language for talking about addiction. https://nida.nih.gov/drug-topics/addiction-science/words-matter-preferred-language-talking-about-addiction.
1084 National Institute on Drug Abuse. (2021). Words matter: Preferred language for talking about addiction. https://nida.nih.gov/drug-topics/addiction-science/words-matter-preferred-language-talking-about-addiction.
1085 National Institute on Drug Abuse. (2021). Words matter: Preferred language for talking about addiction. https://nida.nih.gov/drug-topics/addiction-science/words-matter-preferred-language-talking-about-addiction.
1086 National Institute on Drug Abuse. (2021). Words matter: Preferred language for talking about addiction. https://nida.nih.gov/drug-topics/addiction-science/words-matter-preferred-language-talking-about-addiction.
1087 Ashford, R. D., Brown, A. M., & Curtis, B. (2018). Substance use, recovery, and linguistics: The impact of word choice on explicit and implicit bias. Drug and Alcohol Dependence, 189, 131–138.29913324
1088 Wilke, E., Markon, K. E., Freedland, T. A. (2022). Predictors of client dropout from intensive outpatient treatment for substance use disorders. Research Brief No. 9. Center for Practice Transformation, University of Minnesota.
1089 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol (TIP) Series 33. SAMHSA Publication No. PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
1090 Recovery Answers. (n.d.). Addictionary®. https://www.recoveryanswers.org/addiction-ary/.
1091 Recovery Answers. (n.d.). Addictionary®. https://www.recoveryanswers.org/addiction-ary/.
1092 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1093 Haskell, B. (2022). Identification and evidence-based treatment of post-acute withdrawal syndrome. Journal for Nurse Practitioners, 18(3), 272–275.
1094 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
1095 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1096 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1097 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
1098 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
1099 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1100 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1101 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1102 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1103 Substance Abuse and Mental Health Services Administration. (2019). Enhancing motivation for change in substance use disorder treatment. Treatment Improvement Protocol (TIP) Series 35. SAMHSA Publication No. PEP19-02-01-003. Substance Abuse and Mental Health Services Administration.
1104 Substance Abuse and Mental Health Services Administration. (2010). Protracted withdrawal. Substance Abuse Treatment Advisory, 9(1).
1105 Wakeman, S. E., Larochelle, M. R., Ameli, O., Chaisson, C. E., McPheeters, J. T., Crown, W. H., Azocar, F., & Sanghavi, D. M. (2020). Comparative effectiveness of different treatment pathways for opioid use disorder. JAMA Network Open, 3(2), e1920622.32022884
1106 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1107 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1108 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1109 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1110 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1111 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1112 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications.
1113 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1114 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1115 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1116 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications.
1117 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1118 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1119 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1120 U.S. Food and Drug Administration. (2022). Vivitrol: Prescribing information. https://www.accessdata.fda.gov/drugsatfda_docs/label/2022/021897s057lbl.pdf.
1121 U.S. Food and Drug Administration. (2022). Vivitrol: Prescribing information. https://www.accessdata.fda.gov/drugsatfda_docs/label/2022/021897s057lbl.pdf.
1122 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1123 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1124 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1125 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1126 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1127 U.S. Food and Drug Administration. (2017). Sublocade (buprenorphine extended-release) injection: Prescribing information. https://www.accessdata.fda.gov/drugsatfdadocs/label/2017/209819s000lbl.pdf.
1128 Substance Abuse and Mental Health Services Administration. (2022). Naloxone. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions/naloxone.
1129 Substance Abuse and Mental Health Services Administration. (2022). Naloxone. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions/naloxone.
1130 Substance Abuse and Mental Health Services Administration. (2022). Naloxone. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions/naloxone.
1131 Substance Abuse and Mental Health Services Administration. (2022). Naloxone. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions/naloxone.
1132 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1133 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications.
1134 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1135 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications.
1136 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. https://store.samhsa.gov/product/Medication-for-the-Treatment-of-Alcohol-Use-Disorder-A-Brief-Guide/SMA15-4907.
1137 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications.
1138 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1139 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions#opioid-dependency-medications.
1140 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1141 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1142 Substance Abuse and Mental Health Services Administration. (2015). Medication for the treatment of alcohol use disorder: A brief guide. SAMHSA Publication No. SMA15-4907. Substance Abuse and Mental Health Services Administration.
1143 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. SAMHSA Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1144 Substance Abuse and Mental Health Services Administration. (2021). Medications for opioid use disorder. Treatment Improvement Protocol (TIP) Series 63. Publication No. PEP21-02-01-002. Substance Abuse and Mental Health Services Administration.
1145 Substance Abuse and Mental Health Services Administration. (2022). Medications, counseling, and related conditions. https://www.samhsa.gov/medication-assisted-treatment/medications-counseling-related-conditions.
1146 National Institute on Drug Abuse. (2018). Cognitive-behavioral therapy (alcohol, marijuana, cocaine, methamphetamine, nicotine). In Principles of drug addiction treatment: A research-based guide (3rd ed.). https://nida.nih.gov/sites/default/files/podat-3rdEd-508.pdf.
1147 National Institute on Drug Abuse. (2018). Cognitive-behavioral therapy (alcohol, marijuana, cocaine, methamphetamine, nicotine). In Principles of drug addiction treatment: A research-based guide (3rd ed.). https://nida.nih.gov/sites/default/files/podat-3rdEd-508.pdf.
1148 Madden, E. F., Prevedel, S., Light, T., & Sulzer, S. H. (2021). Intervention stigma toward medications for opioid use disorder: A systematic review. Substance Use & Misuse, 56(14), 2181–2201.34538213
1149 Trivedi, M. H., Walker, R., Ling, W., Dela Cruz, A., Sharma, G., Carmody, T., … Shoptaw, S. (2021). Bupropion and naltrexone in methamphetamine use disorder. New England Journal of Medicine, 384(2), 140–153.33497547
1150 Grim, B. J., & Grim, M. E. (2019). Belief, behavior, and belonging: How faith is indispensable in preventing and recovering from substance abuse. Journal of Religion and Health, 58(5), 1713–1750.31359242
1151 Witkiewitz, K., McCallion, E., & Kirouac, M. (2016). Religious affiliation and spiritual practices: An examination of the role of spirituality in alcohol use and alcohol use disorder. Alcohol Research: Current Reviews, 38(1), 55–58.27159812
1152 Hai, A. H., Wigmore, B., Franklin, C., Shorkey, C., von Sternberg, K., Cole, A. H., Jr., & DiNitto, D. M. (2021). Efficacy of two-way prayer meditation in improving the psychospiritual well-being of people with substance use disorders: A pilot randomized controlled trial. Substance Abuse, 42(4), 832–841.33471629
1153 Ghahremani, D. G. (2017). Craving, prayer, and the brain. American Journal of Drug and Alcohol Abuse, 43(1), 1–3.27712120
1154 Galanter, M., Josipovic, Z., Dermatis, H., Weber, J., & Millard, M. A. (2017). An initial fMRI study on neural correlates of prayer in members of Alcoholics Anonymous. American Journal of Drug and Alcohol Abuse, 43(1), 44–54.27015258
1155 Ghahremani, D. G. (2017). Craving, prayer, and the brain. American Journal of Drug and Alcohol Abuse, 43(1), 1–3.27712120
1156 Bai, Z. (2021). Does frequent prayer help reduce alcohol use? Heterogeneity in religious contexts and drinking styles. Mental Health, Religion & Culture, 24(2), 151–163.
1157 Smoyer, A. B. (2016). Being on the mat: A process evaluation of trauma-informed yoga for women with substance use disorders. Journal of Sociology and Social Welfare, 43(4), 61.
1158 Brooks, J., Lawlor, S., Turetzkin, S., Goodnight, C. W., & Galantino, M. L. (2021). Yoga for substance use disorder in women: A systematic review. International Journal of Yoga Therapy, 31(1), Article 21.
1159 Walia, N., Matas, J., Turner, A., Gonzalez, S., & Zoorob, R. (2021). Yoga for substance use: A systematic review. Journal of the American Board of Family Medicine, 34(5), 964–973.34535521
1160 Brooks, J., Lawlor, S., Turetzkin, S., Goodnight, C. W., & Galantino, M. L. (2021). Yoga for substance use disorder in women: A systematic review. International Journal of Yoga Therapy, 31(1), Article 21.
1161 Greene, D. (2021). Yoga: A holistic approach to addiction treatment and recovery. OBM Integrative and Complementary Medicine, 6(4), 1–1.
1162 Fishbein, D., Miller, S., Herman-Stahl, M., Williams, J., Lavery, B., Markovitz, L., … Johnson, M. (2016). Behavioral and psychophysiological effects of a yoga intervention on high-risk adolescents: A randomized control trial. Journal of Child and Family Studies, 25(2), 518–529.
1163 Walia, N., Matas, J., Turner, A., Gonzalez, S., & Zoorob, R. (2021). Yoga for substance use: A systematic review. Journal of the American Board of Family Medicine, 34(5), 964–973.34535521
1164 Lander, L., Chiasson-Downs, K., Andrew, M., Rader, G., Dohar, S., & Waibogha, K. (2018). Yoga as an adjunctive intervention to medication-assisted treatment with buprenorphine+naloxone. Journal of Addiction Research & Therapy, 9(1), 354.
1165 Greene, D. (2021). Yoga: A holistic approach to addiction treatment and recovery. OBM Integrative and Complementary Medicine, 6(4), 1–1.
1166 Park, C. L., Russell, B. S., & Fendrich, M. (2018). Mind-body approaches to prevention and intervention for alcohol and other drug use/abuse in young adults. Medicines, 5(3), 64.29954058
1167 Walia, N., Matas, J., Turner, A., Gonzalez, S., & Zoorob, R. (2021). Yoga for substance use: A systematic review. Journal of the American Board of Family Medicine, 34(5), 964–973.34535521
1168 Tibbitts, D. C., Aicher, S. A., Sugg, J., Handloser, K., Eisman, L., Booth, L. D., & Bradley, R. D. (2021). Program evaluation of trauma-informed yoga for vulnerable populations. Evaluation and Program Planning, 88, 101946.33901773
1169 Smoyer, A. B. (2016). Being on the mat: A process evaluation of trauma-informed yoga for women with substance use disorders. Journal of Sociology and Social Welfare, 43(4), 61.
1170 Tibbitts, D. C., Aicher, S. A., Sugg, J., Handloser, K., Eisman, L., Booth, L. D., & Bradley, R. D. (2021). Program evaluation of trauma-informed yoga for vulnerable populations. Evaluation and Program Planning, 88, 101946.33901773
1171 Smoyer, A. B. (2016). Being on the mat: A process evaluation of trauma-informed yoga for women with substance use disorders. Journal of Sociology and Social Welfare, 43(4), 61.
1172 Kapoor, A. (2021). Resilience counseling: Building resilience with the help of counselors. https://www.calmsage.com/what-is-resilience-counseling/#:~:text=Resilience%20counseling%20helps%20you%20discover%20who%20you%20arefwhat%20does%20not%20work%20and%20what%20actually%20works.
1173 Rudzinskif K., McDonough, P., Gartner, R., & Strike, C. (2017). Is there room for resilience? A scoping review and critique of substance use literature and its utilization of the concept of resilience. Substance Abuse Treatment, Prevention, and Policy, 12(1), 41.
1174 Rudzinski, K., McDonough, P., Gartner, R., & Strike, C. (2017). Is there room for resilience? A scoping review and critique of substance use literature and its utilization of the concept of resilience. Substance Abuse Treatment, Prevention, and Policy, 12(1), 41.28915841
1175 Friedberg, A., & Malefakis, D. (2018). Resilience, trauma, and coping. Psychodynamic Psychiatry, 46(1), 81–113.29480784
1176 Mehl-Madrona, L., & Mainguy, B. (2014). Introducing healing circles and talking circles into primary care. Permanente Journal, 18(2), 4–9.
1177 Mehl-Madrona, L., & Mainguy, B. (2014). Introducing healing circles and talking circles into primary care. Permanente Journal, 18(2), 4–9.
1178 Healing Justice Project. (n.d.). Restorative justice and the circle process. https://healingjusticeproject.org/circle-process.
1179 Vemireddy, R. (2020). The role of Native American healing traditions within allopathic medicine. Inquiries Journal, 12(12), 1.
1180 Mehl-Madrona, L., & Mainguy, B. (2014). Introducing healing circles and talking circles into primary care. Permanente Journal, 18(2), 4–9.
1181 Vemireddy, R. (2020). The role of Native American healing traditions within allopathic medicine. Inquiries Journal, 12(12), 1.
1182 Marsh, T. N., Coholic, D., Cote-Meek, S., & Najavits, L. M. (2015). Blending Aboriginal and Western healing methods to treat intergenerational trauma with substance use disorder in Aboriginal peoples who live in Northeastern Ontario, Canada. Harm Reduction Journal, 12, 14.25989833
1183 Vemireddy, R. (2020). The role of Native American healing traditions within allopathic medicine. Inquiries Journal, 12(12), 1.
1184 Vemireddy, R. (2020). The role of Native American healing traditions within allopathic medicine. Inquiries Journal, 12(12), 1.
1185 Substance Abuse and Mental Health Services Administration. (n.d.). SAMHSA's working definition of recovery from mental disorders and substance use disorders. https://www.naadac.org/assets/2416/samhsaworking-definitionofrecovery.pdf#:~:text=Through%20the%20Recovery%20Support%20Strategic%20Initiative%2C%20SAMHSA%20hasfHome%3A%20a%20stable%20and%20safe%20place%20to%20live%3B.
1186 Substance Abuse and Mental Health Services Administration. (2022). Recovery and recovery support. https://www.samhsa.gov/find-help/recovery.
1187 Substance Abuse and Mental Health Services Administration. (n.d.). SAMHSA's working definition of recovery from mental disorders and substance use disorders. https://www.naadac.org/assets/2416/samhsaworking-definitionofrecovery.pdf#:~:text=Through%20the%20Recovery%20Support%20Strategic%20Initiative%2C%20SAMHSA%20has,Home%3A%20a%20stable%20and%20safe%20place%20to%20live%3B.
1188 Substance Abuse and Mental Health Services Administration. (2022). Recovery and recovery support. https://www.samhsa.gov/find-help/recovery.
1189 Substance Abuse and Mental Health Services Administration. (n.d.). SAMHSA's working definition of recovery from mental disorders and substance use disorders. https://www.naadac.org/assets/2416/samhsaworking-definitionofrecovery.pdf#:~:text=Through%20the%20Recovery%20Support%20Strategic%20Initiative%2C%20SAMHSA%20hasfHome%3A%20a%20stable%20and%20safe%20place%20to%20live%3B.
1190 Substance Abuse and Mental Health Services Administration. (2012). SAMHSA's working definition of recovery: 10 guiding principles of recovery. https://store.samhsa.gov/sites/default/files/d7/priv/pep12-recdef.pdf.
1191 Wu, L. T., Ghitza, U. E., Zhu, H., Spratt, S., Swartz, M., & Mannelli, P. (2018). Substance use disorders and medical comorbidities among high-need, high-risk patients with diabetes. Drug and Alcohol Dependence, 186, 86–93.29554592
1192 Wu, L. T., Ghitza, U. E., Zhu, H., Spratt, S., Swartz, M., & Mannelli, P. (2018). Substance use disorders and medical comorbidities among high-need, high-risk patients with diabetes. Drug and Alcohol Dependence, 186, 86–93.29554592
1193 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03-3824. Substance Abuse and Mental Health Services Administration.
1194 Substance Abuse and Mental Health Services Administration. (2019). Get connected: Linking older adults with resources on medication, alcohol, and mental health. HHS Publication No. (SMA) 03-3824. Substance Abuse and Mental Health Services Administration.
1195 Centers for Medicare & Medicaid Services. (2014). From coverage to care: A roadmap to better care and a healthier you. https://marketplace.cms.gov/outreach-and-education/downloads/c2c-pick-a-provider.pdf.
1196 Centers for Medicare & Medicaid Services. (2014). From coverage to care: A roadmap to better care and a healthier you. https://marketplace.cms.gov/outreach-and-education/downloads/c2c-pick-a-provider.pdf.
1197 Chang G. (2020). Maternal substance use: Consequences, identification, and interventions. Alcohol Research: Current Reviews, 40(2), 06.
1198 Hirai, A. H., Ko, J. Y., Owens, P. L., Stocks, C., & Patrick, S. W. (2021). Neonatal abstinence syndrome and maternal opioid-related diagnoses in the US, 2010-2017. JAMA, 325(2), 146–155.33433576
1199 Forray, A., & Foster, D. (2015). Substance use in the perinatal period. Current Psychiatry Reports, 17(11), 91.26386836
1200 American Society of Addiction Medicine and the American College of Obstetricians and Gynecologists. (2017). Clinical recommendations: Opioid use and opioid use disorder in pregnancy. https://www.asam.org/quality-care/clinical-recommendations/OUD-in-Pregnancy.
1201 American Society of Addiction Medicine and the American College of Obstetricians and Gynecologists. (2017). Clinical recommendations: Opioid use and opioid use disorder in pregnancy. https://www.asam.org/quality-care/clinical-recommendations/OUD-in-Pregnancy.
1202 American Society of Addiction Medicine and the American College of Obstetricians and Gynecologists. (2017). Clinical recommendations: Opioid use and opioid use disorder in pregnancy. https://www.asam.org/quality-care/clinical-recommendations/OUD-in-Pregnancy.
1203 Haight, S. C., Ko, J. Y., Tong, V. T., Bohm, M. K., & Callaghan, W. M. (2018). Opioid use disorder documented at delivery hospitalization—United States, 1999-2014. Morbidity and Mortality Weekly Report, 67(31), 845.30091969
1204 Chang G. (2020). Maternal substance use: Consequences, identification, and interventions. Alcohol Research: Current Reviews, 40(2), 06.
1205 Chang G. (2020). Maternal substance use: Consequences, identification, and interventions. Alcohol Research: Current Reviews, 40(2), 06.
1206 Substance Abuse and Mental Health Services Administration. (2022). Marijuana and pregnancy. https://www.samhsa.gov/marijuana/marijuana-pregnancy#:~:text=No%20amount%20of%20marijuana%20hasffor%20them%20or%20their%20children.
1207 American Society of Addiction Medicine and the American College of Obstetricians and Gynecologists. (2017). Clinical recommendations: Opioid use and opioid use disorder in pregnancy. https://www.asam.org/quality-care/clinical-recommendations/OUD-in-Pregnancy.
1208 American Society of Addiction Medicine and the American College of Obstetricians and Gynecologists. (2017). Clinical recommendations: Opioid use and opioid use disorder in pregnancy. https://www.asam.org/quality-care/clinical-recommendations/OUD-in-Pregnancy.
1209 American College of Obstetricians and Gynecologists. (2020). Opposition to criminalization of individuals during pregnancy and the postpartum period. https://www.acog.org/clinical-information/policy-and-position-statements/statements-of-policy/2020/opposition-criminalization-of-individuals-pregnancy-and-postpartum-period#:~:text=Clear%20evidence%20exists%20that%20criminalizationfinfant%20(7%2C%209).
1210 Svikis, D. S., Golden, A. S., Huggins, G. R., Pickens, R. W., McCaul, M. E., Velez, M. L., … Ball, C. E. (1997). Cost-effectiveness of treatment for drug-abusing pregnant women. Drug and Alcohol Dependence, 45(1-2), 105–113.9179512
1211 HIV.gov. (2018). Substance use and HIV risk. https://www.hiv.gov/hiv-basics/hiv-prevention/reducing-risk-from-alcohol-and-drug-use/substance-use-and-hiv-risk.
1212 Substance Abuse and Mental Health Services Administration. (2022). Harm reduction. https://www.samhsa.gov/find-help/harm-reduction.
1213 Centers for Disease Control and Prevention. (2022). Condom distribution structural intervention (CDSI). https://www.cdc.gov/hiv/effective-interventions/prevent/condom-distribution-programs/index.html.
1214 Iversen, J., Long, P., Lutnick, A., & Maher, L. (2021). Patterns and epidemiology of illicit drug use among sex workers globally: A systematic review. In S. M. Goldenberg, R. Morgan Thomas, A. Forbes, & S. Baral (Eds.), Sex work, health, and human rights: Global inequities, challenges, and opportunities for action (pp. 95–118). Springer.
1215 Iversen, J., Long, P., Lutnick, A., & Maher, L. (2021). Patterns and epidemiology of illicit drug use among sex workers globally: A systematic review. In S. M. Goldenberg, R. Morgan Thomas, A. Forbes, & S. Baral (Eds.), Sex work, health, and human rights: Global inequities, challenges, and opportunities for action (pp. 95–118). Springer.
1216 American Hospital Association. (2017). Transportation and the role of hospitals. https://www.aha.org/system/files/hpoe/Reports-HPOE/2017/sdoh-transportation-role-of-hospitals.pdf.
1217 Bryant, S. (2021). Transportation barriers to medical appointments. https://www.montgomerycountymd.gov/OLO/Resources/Files/2021Reports/OLOReport2021-11.pdf.
1218 Biancarelli, D. L., Biello, K. B., Childs, E., Drainoni, M., Salhaney, P., Edeza, A., … Bazzi, A. R. (2019). Strategies used by people who inject drugs to avoid stigma in healthcare settings. Drug and Alcohol Dependence, 198, 80–86.30884432
1219 Substance Abuse and Mental Health Services Administration. (2021). Treatment for stimulant use disorders. Treatment Improvement Protocol 33. Publication No: PEP21-02-01-004. Substance Abuse and Mental Health Services Administration.
1220 Mahboub, N., Rizk, R., Karavetian, M., & de Vries, N. (2020). Nutritional status and eating habits of people who use drugs and/or are undergoing treatment for recovery: A narrative review. Nutrition Reviews, 79(6), 627–635.
1221 Sason, A., Adelson, M., Herzman-Harari, S., & Peles, E. (2018). Knowledge about nutrition, eating habits and weight reduction intervention among methadone maintenance treatment patients. Journal of Substance Abuse Treatment, 86, 52–59.29415851
1222 Mahboub, N., Rizk, R., Karavetian, M., & de Vries, N. (2020). Nutritional status and eating habits of people who use drugs and/or are undergoing treatment for recovery: A narrative review. Nutrition Reviews, 79(6), 627–635.
1223 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers. (pp. 21–42). Elsevier.
1224 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers. (pp. 21–42). Elsevier.
1225 Chavez, M. N., & Rigg, K. K. (2020). Nutritional implications of opioid use disorder: A guide for drug treatment providers. Psychology of Addictive Behaviors, 34(6), 699–707.32202820
1226 Savoie-Roskos, M. R., Yaugher, A. C., Condie, A. W., Murza, G., Voss, M. W., & Atisme, K. (n.d.). Diet, nutrition, and substance use disorder. Utah State University Extension. Retrieved December 1, 2022, from https://extension.usu.edu/heart/research/diet-nutriton-and-substance-use-disorder.
1227 Formplus. (2022). What is nutritional assessment? https://www.formpl.us/blog/nutritional-assessment#:~:text=%20Types%20of%20Nutritional%20Assessment%20%201%20Anthropometricfthe%20simplest%20and%20most%20practical%20method…%20More%20.
1228 Feltner, C., Peat, C., Reddy, S., Riley, S., Berkman, N., Middleton, J. C., … Jonas, D. E. (2022). Screening for eating disorders in adolescents and adults: An evidence review for the U.S. preventive services task force. Evidence Synthesis No. 212. AHRQ Publication No. 21-05284-EF-1. Agency for Healthcare Research and Quality.
1229 Houchins, J. R., Kelly, M. M., & Phillips, K. A. (2019). Motives for illicit drug use among individuals with body dysmorphic disorder. Journal of Psychiatric Practice®, 25(6), 427–436.31821219
1230 Ibrahim, N., Alameddine, M., Brennan, J., Sessine, M., Holliday, C., & Ghaferi, A. A. (2019). New onset alcohol use disorder following bariatric surgery. Surgical Endoscopy, 33(8), 2521–2530.30350107
1231 Chavez, M. N., & Rigg, K. K. (2020). Nutritional implications of opioid use disorder: A guide for drug treatment providers. Psychology of Addictive Behaviors, 34(6), 699–707.32202820
1232 Wiss, D. A. (2019). A biopsychosocial overview of the opioid crisis: Considering nutrition and gastrointestinal health. Frontiers in Public Health, 7, 193.31338359
1233 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers. (pp. 21–42). Elsevier.
1234 Crane, M. (n.d.). Nutrition for addiction recovery. American Addiction Centers. Retrieved December 1, 2022, from https://recovery.org/treatment-therapy/nutrition/.
1235 Gay, I. C., Tran, D. T., & Paquette, D. W. (2018). Alcohol intake and periodontitis in adults aged > 30 years: NHANES 2009-2012. Journal of Periodontology, 89(6), 625–634.29572839
1236 Gupta, M., Gokarakonda, S. B., & Attia, F. N. (2022). Withdrawal syndromes. In StatPearls. StatPearls Publishing.
1237 Crane, M. (n.d.). Nutrition for addiction recovery. American Addiction Centers. Retrieved December 1, 2022, from https://recovery.org/treatment-therapy/nutrition/.
1238 Bahdila, D., Aldosari, M., Abdullah, A., Nelson, J. L., Hegazi, F., Badamia, R., … Agaku, I. T. (2020). Cocaine, polysubstance abuse, and oral health outcomes, NHANES 2009-2014. Journal of Periodontology, 91(8), 1039–1048.31919844
1239 Mahboub, N., Rizk, R., Karavetian, M., & de Vries, N. (2020). Nutritional status and eating habits of people who use drugs and/or are undergoing treatment for recovery: A narrative review. Nutrition Reviews, 79(6), 627–635.
1240 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers. (pp. 21–42). Elsevier.
1241 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers. (pp. 21–42). Elsevier.
1242 Chavez, M. N., & Rigg, K. K. (2020). Nutritional implications of opioid use disorder: A guide for drug treatment providers. Psychology of Addictive Behaviors, 34(6), 699–707.32202820
1243 Vertava Health. (n.d.). Nutrition and wellness for drug and alcohol addiction treatment. Retrieved December 1, 2022, from https://vertavahealth.com/addiction-treatment/nutrition-wellness/.
1244 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers (pp. 21–42). Elsevier.
1245 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers (pp. 21–42). Elsevier.
1246 Chavez, M. N., & Rigg, K. K. (2020). Nutritional implications of opioid use disorder: A guide for drug treatment providers. Psychology of Addictive Behaviors, 34(6), 699–707.32202820
1247 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers (pp. 21–42). Elsevier.
1248 Chavez, M. N., & Rigg, K. K. (2020). Nutritional implications of opioid use disorder: A guide for drug treatment providers. Psychology of Addictive Behaviors, 34(6), 699–707.32202820
1249 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers (pp. 21–42). Elsevier.
1250 Nelson, M. (n.d.). How substance abuse disrupts nutrition. Advanced Recovery Systems. https://www.drugrehab.com/guides/nutrition/.
1251 Wiss, D. A. (2019). The role of nutrition in addiction recovery: What we know and what we don't. In I. Danovitch & L. J. Mooney (Eds.), The assessment and treatment of addiction: Best practices and new frontiers (pp. 21–42). Elsevier.
1252 Savoie-Roskos, M. R., Yaugher, A. C., Condie, A. W., Murza, G., Voss, M. W., & Atisme, K. (n.d.). Diet, nutrition, and substance use disorder. Utah State University Extension. Retrieved December 1, 2022, from https://extension.usu.edu/heart/research/diet-nutriton-and-substance-use-disorder.
1253 Abrantes, A. M., & Blevins, C. E. (2019). Exercise in the context of substance use treatment: Key issues and future directions. Current Opinion in Psychology, 30, 103–108.31079012
1254 Ashdown-Franks, G., Firth, J., Carney, R., Carvalho, A. F., Hallgren, M., Koyanagi, A., … Stubbs, B. (2020). Exercise as medicine for mental and substance use disorders: A metareview of the benefits for neuropsychiatric and cognitive outcomes. Sports Medicine, 50(1), 151–170.31541410
1255 Ashdown-Franks, G., Firth, J., Carney, R., Carvalho, A. F., Hallgren, M., Koyanagi, A., … Stubbs, B. (2020). Exercise as medicine for mental and substance use disorders: A metareview of the benefits for neuropsychiatric and cognitive outcomes. Sports Medicine, 50(1), 151–170.31541410
1256 Thompson, T. P., Horrell, J., Taylor, A. H., Wanner, A., Husk, K., Wei, Y., Wallace, G. (2020). Physical activity and the prevention, reduction, and treatment of alcohol and other drug use across the lifespan (The PHASE review): A systematic review. Mental Health and Physical Activity, 19, 100360.33020704
1257 Brellenthin, A. G., & Lee, D. C. (2018). Physical activity and the development of substance use disorders: Current knowledge and future directions. Progress in Preventive Medicine, 3(3), e0018.30345414
1258 Abrantes, A. M., & Blevins, C. E. (2019). Exercise in the context of substance use treatment: Key issues and future directions. Current Opinion in Psychology, 30, 103–108.31079012
1259 Centers for Disease Control and Prevention. (2022). Benefits of physical activity. https://www.cdc.gov/physicalactivity/basics/pa-health/index.htm.
1260 Ashdown-Franks, G., Firth, J., Carney, R., Carvalho, A. F., Hallgren, M., Koyanagi, A., … Stubbs, B. (2020). Exercise as medicine for mental and substance use disorders: A metareview of the benefits for neuropsychiatric and cognitive outcomes. Sports Medicine, 50(1), 151–170.31541410
1261 Ashdown-Franks, G., Firth, J., Carney, R., Carvalho, A. F., Hallgren, M., Koyanagi, A., … Stubbs, B. (2020). Exercise as medicine for mental and substance use disorders: A metareview of the benefits for neuropsychiatric and cognitive outcomes. Sports Medicine, 50(1), 151–170.31541410
1262 Brellenthin, A. G., & Lee, D. C. (2018). Physical activity and the development of substance use disorders: Current knowledge and future directions. Progress in Preventive Medicine, 3(3), e0018.30345414
1263 Ashdown-Franks, G., Firth, J., Carney, R., Carvalho, A. F., Hallgren, M., Koyanagi, A., … Stubbs, B. (2020). Exercise as medicine for mental and substance use disorders: A metareview of the benefits for neuropsychiatric and cognitive outcomes. Sports Medicine, 50(1), 151–170.31541410
1264 Thompson, T. P., Horrell, J., Taylor, A. H., Wanner, A., Husk, K., Wei, Y., Wallace, G. (2020). Physical activity and the prevention, reduction, and treatment of alcohol and other drug use across the lifespan (The PHASE review): A systematic review. Mental Health and Physical Activity, 19, 100360.33020704
1265 Brellenthin, A. G., & Lee, D. C. (2018). Physical activity and the development of substance use disorders: Current knowledge and future directions. Progress in Preventive Medicine, 3(3), e0018.30345414
1266 U.S. Department of Health and Human Services. (2018). Health care providers: Talk to your patients about physical activity. https://health.gov/sites/default/files/2021-02/PAG_MYW_FactSheet_HCP_508c.pdf.
1267 U.S. Department of Health and Human Services. (n.d.). Walk. Run. Dance. Play. What's your move? https://health.gov/moveyourway#adults.
1268 Abrantes, A. M., & Blevins, C. E. (2019). Exercise in the context of substance use treatment: Key issues and future directions. Current Opinion in Psychology, 30, 103–108.31079012
1269 Abrantes, A. M., & Blevins, C. E. (2019). Exercise in the context of substance use treatment: Key issues and future directions. Current Opinion in Psychology, 30, 103–108.31079012
1270 Abrantes, A. M., & Blevins, C. E. (2019). Exercise in the context of substance use treatment: Key issues and future directions. Current Opinion in Psychology, 30, 103–108.31079012
1271 Recovery Research Institute. (n.d.). Motivational interviewing and enhancement therapies. Retrieved December 1, 2022, from https://www.recoveryanswers.org/resource/motivational-interviewing-motivational-enhancement-therapies-mi-met/.
1272 Abrantes, A. M., & Blevins, C. E. (2019). Exercise in the context of substance use treatment: Key issues and future directions. Current Opinion in Psychology, 30, 103–108.31079012
1273 Chakravorty, S., Vandrey, R. G., He, S., & Stein, M. D. (2018). Sleep management among patients with substance use disorders. Medical Clinics, 102(4), 733–743.29933826
1274 Miller, M. B., Donahue, M. L., Carey, K. B., & Scott-Sheldon, L. A. (2017). Insomnia treatment in the context of alcohol use disorder: A systematic review and meta-analysis. Drug and Alcohol Dependence, 181, 200–207.29096290
1275 American Academy of Sleep Medicine.™ (2020). Healthy sleep habits. https://sleepeducation.org/healthy-sleep/healthy-sleep-habits/.
1276 Sleep Foundation. (2022). Sleep hygiene. https://www.sleepfoundation.org/sleep-hygiene.
1277 Polcin, D. L., & Korcha, R. (2017). Housing status, psychiatric symptoms, and substance abuse outcomes among sober living house residents over 18 months. Addictive Disorders & Their Treatment, 16(3), 138–150.29056875
1278 Chavira, D., & Jason, L. (2017). The impact of limited housing opportunities on formerly incarcerated people in the context of addiction recovery. Journal of Addictive Behaviors and Therapy, 1(1), 02.28713877
1279 Magwood, O., Salvalaggio, G., Beder, M., Kendall, C., Kpade, V., Daghmach, W., … Pottie, K. (2020). The effectiveness of substance use interventions for homeless and vulnerably housed persons: A systematic review of systematic reviews on supervised consumption facilities, managed alcohol programs, and pharmacological agents for opioid use disorder. PLoS One, 15(1), e0227298.31945092
1280 Baker, O., Wellington, C., Price, C. R., Tracey, D., Powell, L., Loffredo, S., Moscariello, S., & Meyer, J. P. (2023). Experience delivering an integrated service model to people with criminal justice system involvement and housing insecurity. BMC Public Health, 23(1), 222.36732685
1281 Duque, R. B. (2021). Black health matters too… especially in the era of Covid-19: How poverty and race converge to reduce access to quality housing, safe neighborhoods, and health and wellness services and increase the risk of co-morbidities associated with global pandemics. Journal of Racial and Ethnic Health Disparities, 8(4), 1012–1025.32946069
1282 Substance Abuse and Mental Health Services Administration (2022, September 26). Affordable housing models and recovery. https://www.samhsa.gov/homelessness-programs-resources/hpr-resources/affording-housing-models-recovery.
1283 Magwood, O., Salvalaggio, G., Beder, M., Kendall, C., Kpade, V., Daghmach, W., … Pottie, K. (2020). The effectiveness of substance use interventions for homeless and vulnerably housed persons: A systematic review of systematic reviews on supervised consumption facilities, managed alcohol programs, and pharmacological agents for opioid use disorder. PLoS One, 15(1), e0227298.31945092
1284 Pfefferle, S. G., Karon, S. S., & Wyant, B. (2019). Choice matters: Housing models that may promote recovery for individuals and families facing opioid use disorder. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
1285 Rezansoff, S. N., Moniruzzaman, A., Fazel, S., McCandless, L., Procyshyn, R., & Somers, J. M. (2017). Housing First improves adherence to antipsychotic medication among formerly homeless adults with schizophrenia: Results of a randomized controlled trial. Schizophrenia Bulletin, 43(4), 852–861.27665002
1286 Pfefferle, S. G., Karon, S. S., & Wyant, B. (2019). Choice matters: Housing models that may promote recovery for individuals and families facing opioid use disorder. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
1287 Magwood, O., Salvalaggio, G., Beder, M., Kendall, C., Kpade, V., Daghmach, W., … Pottie, K. (2020). The effectiveness of substance use interventions for homeless and vulnerably housed persons: A systematic review of systematic reviews on supervised consumption facilities, managed alcohol programs, and pharmacological agents for opioid use disorder. PLoS One, 15(1), e0227298.31945092
1288 Substance Abuse and Mental Health Services Administration (n.d.). Recovery housing: Best practices and suggested guidelines. https://www.samhsa.gov/sites/default/files/housing-best-practices-100819.pdf.
1289 Pfefferle, S. G., Karon, S. S., & Wyant, B. (2019). Choice matters: Housing models that may promote recovery for individuals and families facing opioid use disorder. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
1290 Substance Abuse and Mental Health Services Administration (n.d.). Recovery housing: Best practices and suggested guidelines. https://www.samhsa.gov/sites/default/files/housing-best-practices-100819.pdf.
1291 National Council for Behavioral Health. (n.d.). Building recovery: State policy guide for supporting recovery housing. https://www.thenationalcouncil.org/resources/building-recovery-state-policy-guide-for-supporting-recovery-housing/.
1292 National Association of Recovery Residences. (2012). A primer on recovery residences: FAQs from the National Association of Recovery Residences. https://narronline.org/wp-content/uploads/2014/06/Primer-on-Recovery-Residences-09-20-2012a.pdf.
1293 National Council for Behavioral Health. (n.d.). Building recovery: State policy guide for supporting recovery housing. https://www.thenationalcouncil.org/resources/building-recovery-state-policy-guide-for-supporting-recovery-housing/.
1294 National Alliance for Recovery Residences. (2018). NARR standard 3.0. https://narronline.org/wp-content/uploads/2018/11/NARRStandardV.3.0release11-2018.pdf.
1295 Substance Abuse and Mental Health Services Administration. (n.d.). Recovery housing: Best practices and suggested guidelines. https://www.samhsa.gov/sites/default/files/housing-best-practices-100819.pdf.
1296 National Association of Recovery Residences. (2012). A primer on recovery residences: FAQs from the National Association of Recovery Residences. https://narronline.org/wp-content/uploads/2014/06/Primer-on-Recovery-Residences-09-20-2012a.pdf.
1297 HUD Exchange. (n.d.). Continuum of care (CoC) program eligibility requirements. https://www.hudexchange.info/programs/coc/coc-program-eligibility-requirements/#:~:text=Transitional%20housing%20(TH)%20is%20designedfhousing%20with%20accompanying%20supportive%20services.
1298 Homeless Hub. (n.d.). Transitional housing. Retrieved December, 1, 2022, from https://www.homelesshub.ca/solutions/housing-accommodation-and-supports/transitional-housing.
1299 Homeless Hub. (n.d.). Transitional housing. Retrieved December 1, 2022, from https://www.homelesshub.ca/solutions/housing-accommodation-and-supports/transitional-housing.
1300 Aubry, T., Bloch, G., Brcic, V., Saad, A., Magwood, O., Abdalla, T., … Pottie, K. (2020). Effectiveness of permanent supportive housing and income assistance interventions for homeless individuals in high-income countries: A systematic review. Lancet, Public Health, 5(6), e342–e360.32504587
1301 Substance Abuse and Mental Health Services Administration. (2021). Behavioral health services for people who are homeless. Advisory. SAMHSA Publication No. PEP20-06-04-003. Substance Abuse and Mental Health Services Administration.
1302 National Alliance to End Homelessness. (n.d.). Housing First fact sheet. https://endhomelessness.org/wp-content/uploads/2022/02/Housing-First-Fact-SheetFeb-2022.pdf.
1303 Substance Abuse and Mental Health Services Administration. (2021). Behavioral health services for people who are homeless. Advisory. SAMHSA Publication No. PEP20-06-04-003. Substance Abuse and Mental Health Services Administration.
1304 Pfefferle, S. G., Karon, S. S., & Wyant, B. (2019). Choice matters: Housing models that may promote recovery for individuals and families facing opioid use disorder. U.S. Department of Health and Human Services, Office of the Assistant Secretary for Planning and Evaluation.
1305 HUD Exchange. (2022). Homelessness prevention. https://www.hudexchange.info/homelessness-assistance/coc-esg-virtual-binders/esg-program-components/homelessness-prevention/.
1306 Shinn, M., & Cohen, R. (2019). Homelessness prevention: A review of the literature. http://www.evidenceonhomelessness.com/wp-content/uploads/2019/02/Homelessness_Prevention_Literature_Synthesis.pdf.
1307 Shinn, M., & Cohen, R. (2019). Homelessness prevention: A review of the literature. http://www.evidenceonhomelessness.com/wp-content/uploads/2019/02/Homelessness_Prevention_Literature_Synthesis.pdf.
1308 Corporation for Supportive Housing. (n.d.). Health centers and coordinated entry: How and why to engage with local homeless systems. Retrieved December 1, 2022, from https://www.csh.org/wp-content/uploads/2017/05/Coordinated-Entry-and-Health-Centers-1.pdf.
1309 U.S. Department of Housing and Urban Development. (n.d.). Coordinated entry: Core elements. https://files.hudexchange.info/resources/documents/Coordinated-Entry-Core-Elements.pdf.
1310 MassHousing. (n.d.). Housing stability. Retrieved June 13, 2023, from https://www.masshousing.com/en/programs-outreach/housing-stability.
1311 Pallatino, C., Chang, J. C., & Krans, E. E. (2021). The intersection of intimate partner violence and substance use among women with opioid use disorder. Substance Abuse, 42(2), 197–204.31638868
1312 National Network to End Domestic Violence. (2013). Transitional housing: Models & rent structures. https://nnedv.org/wp-content/uploads/2019/07/Library_TH_2018_Housing_Models_Rent_Structures.pdf.
1313 U.S. Department of Housing and Urban Development. (n.d.). Rapid re-housing. https://files.hudexchange.info/resources/documents/Rapid-Re-Housing-Brief.pdf.
1314 National Low Income Housing Coalition. (2022). The gap: A shortage of affordable rental homes. https://nlihc.org/gap#:~:text=The%20U.S.%20has%20a%20shortage,extremely%20low%2Dincome%20renter%20households.
1315 National Low Income Housing Coalition. (2022). The gap: A shortage of affordable rental homes. https://nlihc.org/gap#:~:text=The%20U.S.%20has%20a%20shortage,extremely%20low%2Dincome%20renter%20households.
1316 U.S. Department of Housing and Urban Development. (n.d.). HUD's public housing program. Retrieved December 1, 2022, from https://www.hud.gov/topics/rentalassistance/phprog#:~:text=WHAT%20IS%20PUBLIC%20HOUSING%3F,rise%20apartments%20for%20elderly%20families.
1317 U.S. Department of Housing and Urban Development. (n.d.). Housing Choice vouchers fact sheet. Retrieved December 1, 2022, from https://www.hud.gov/topics/housingchoicevoucherprogramsection8#hcv01.
1318 U.S. Department of Housing and Urban Development. (n.d.). Housing Choice vouchers fact sheet. Retrieved December 1, 2022, from https://www.hud.gov/topics/housing_choice_voucher_program_section_8#hcv01.
1319 Edemekong, P. F., Bomgaars D. L., Sukumaran S., & Schoo, C. (2022). Activities of daily living. In: StatPearls [Internet]. StatPearls Publishing.
1320 Substance Abuse and Mental Health Services Administration. (2022). Recovery and recovery support. https://www.samhsa.gov/find-help/recovery.
1321 McKay, J. R. (2016). Making the hard work of recovery more attractive for those with substance use disorders. Addiction, 112, 751–757.27535787
1322 Jayawickreme, E., Infurna, F. J., Alajak, K., Blackie, L., Chopik, W. J., Chung, J. M., … Zonneveld, R. (2021). Post-traumatic growth as positive personality change: Challenges, opportunities, and recommendations. Journal of Personality, 89(1), 145–165.32897574
1323 Dunlop, W. L., & Tracy, J. L. (2013). Sobering stories: Narratives of self-redemption predict behavioral change and improved health among recovering alcoholics. Journal of Personality and Social Psychology, 104(3), 576–590.23437925
1324 Subhani, M., Talat, U., Knight, H., Morling, J. R., Jones, K. A., Aithal, G. P., … Rennick-Egglestone, S. (2022). Characteristics of alcohol recovery narratives: Systematic review and narrative synthesis. PLoS One, 17(5), e0268034.35511789
1325 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1326 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1327 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1328 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1329 Gutierrez, D., Dorais, S., & Goshorn, J. R. (2020). Recovery as life transformation: Examining the relationships between recovery, hope, and relapse. Substance Use & Misuse, 55(12), 1949–1957.32567447
1330 Frings, D., & Albery, P. (2015). The social identity model of cessation maintenance: Formulation and initial evidence. Addictive Behaviors, 44, 35–75.25468675
1331 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1332 Gutierrez, D., Dorais, S., & Goshorn, J. R. (2020). Recovery as life transformation: Examining the relationships between recovery, hope, and relapse. Substance Use & Misuse, 55(12), 1949–1957.32567447
1333 Beckwith, M., Best, D., Lubman, D., Dingle, G., & Perryman, C. (2015). Predictors of flexibility in social identity among people entering a therapeutic community for substance abuse. Alcohol Treatment Quarterly, 33, 93–104.
1334 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1335 Dingle, G. A., Stark, C., Cruwys, T., & Best, D. (2015). Breaking good: Breaking ties with social groups may be good for recovery from substance misuse. British Journal of Social Psychology, 54, 236–254.25209252
1336 Dingle, G. A., Cruwys, T., & Frings, D. (2015). Social identities as pathways into and out of addiction. Frontiers in Psychology, 6, 1795.26648882
1337 Earnshaw, V. A. (2020). Stigma and substance use disorders: A clinical, research, and advocacy agenda. American Psychologist, 75(9), 1300–1311.33382299
1338 Collinson, B., & Best, D. (2019). Promoting recovery from substance misuse through engagement with community assets: Asset based community engagement. Substance Abuse: Research and Treatment, 13, 1–14.
1339 Best, D., Beckwith, M., Haslam, C., Haslam, S. A., Jetten, J., Mawson, E., & Lubman, D. (2015). Overcoming alcohol and other drug addiction as a process of social identity transition: The social identity model of recovery (SIMOR). Addiction Research and Theory, 24(2), 111–123.
1340 Collinson, B., & Best, D. (2019). Promoting recovery from substance misuse through engagement with community assets: Asset based community engagement. Substance Abuse: Research and Treatment, 13, 1–14.
1341 Earnshaw, V. A. (2020). Stigma and substance use disorders: A clinical, research, and advocacy agenda. American Psychologist, 75(9), 1300–1311.33382299
1342 Crutchfield, D. A., & Guss, C. D. (2018). Achievement linked to recovery from addiction: Discussing education, vocation, and non-addict identity. Alcoholism Treatment Quarterly, 37(3), 1–18.
1343 Smith, J. (2021, December 29). How to stay sober in college: Tips and resources. Addictionresources.net.
1344 Association of Recovery in Higher Education. (2022). Standards and recommendations. https://collegiaterecovery.org/standards-recommendations/.
1345 Magura, S., & Marshall, T. (2020). The effectiveness of interventions intended to improve employment outcomes for persons with substance use disorder: An updated systematic review. Substance Use & Misuse, 55(13), 2230–2236.32781876
1346 Harrison, J., Krieger, M. J., & Johnson, H. A. (2020). Review of individual placement and support employment intervention for persons with substance use disorder. Substance Use & Misuse, 55(4), 636–643.31782349
1347 Vilsaint, C. L., Hoffman, L. A., & Kelly, J. F. (2020). Perceived discrimination in addiction recovery: Assessing the prevalence, nature, and correlates using a novel measure in a U.S. national sample. Drug and Alcohol Dependence, 206, 107667.31780300
1348 Eddie, D., Vilsaint, C. L., Hoffman, L. A., Bergman, B. G., Kelly, J. F., & Hoeppner, B. B. (2020). From working on recovery to working in recovery: Employment status among a nationally representative U.S. sample of individuals who have resolved a significant alcohol or other drug problem. Journal of Substance Abuse Treatment, 113, 108000.32359673
1349 Substance Abuse and Mental Health Services Administration. (2021). Substance use disorders recovery with a focus on employment and education. HHS Publication No. PEP21-PL-Guide-6. National Mental Health and Substance Use Policy Laboratory. Substance Abuse and Mental Health Services Administration.
1350 Peer Recovery Center of Excellence. (n.d.). Recovery friendly workplace toolkit. Retrieved December 1, 2022, from https://peerrecoverynow.org/product/recovery-friendly-workplace-toolkit/.
1351 Centers for Disease Control and Prevention. (2020, July 27). Workplace supported recovery program. National Institute for Occupational Safety and Health.
1352 Sigurdsson, S. O., Ring, B. M., O'Reilly, K., & Silverman, K. (2012). Barriers to employment among unemployed drug users: Age predicts severity. American Journal of Drug and Alcohol Abuse, 38(6), 580–587.22242680
1353 Crutchfield, D. A., & Güss, C. D. (2019). Achievement linked to recovery from addiction: Discussing education, vocation, and non-addict identity. Alcoholism Treatment Quarterly, 37(3), 359–376.
1354 Sahker, E., Ali, S. R., & Arndt, S. (2019). Employment recovery capital in the treatment of substance use disorders: Six-month follow-up observations. Drug and Alcohol Dependence, 205, 107624.31645013
1355 ADA National Network. (2020). The ADA, addiction, recovery, and employment. https://adata.Org/factsheet/ada-addiction-recovery-and-employment.
1356 Ghetti, C., Chen, X. J., Brenner, A. K., Hakvoort, L. G., Lien, L., Fachner, J., & Gold, C. (2022). Music therapy for people with substance use disorders. Cochrane Database of Systematic Reviews, 5(5), CD012576.35532044
1357 Silverman, M. J. (2022). A cluster-randomized trial comparing songwriting and recreational music therapy via craving and withdrawal in adults on a detoxification unit. Substance Use & Misuse, 57(5), 759–768.35156503
1358 Ghetti, C., Chen, X. J., Brenner, A. K., Hakvoort, L. G., Lien, L., Fachner, J., & Gold, C. (2022). Music therapy for people with substance use disorders. Cochrane Database of Systematic Reviews, 5(5), CD012576.35532044
1359 Pinhasi-Vittorio, L. (2018). Writing, sharing, and healing: The interplay of literacy in the healing journey of the recovering from substance abuse. Journal of Poetry Therapy, 31(4), 209–223.
1360 Pinhasi-Vittorio, L. (2018). Writing, sharing, and healing: The interplay of literacy in the healing journey of the recovering from substance abuse. Journal of Poetry Therapy, 31, 1–15.
1361 Krentzman, A. R., Hoeppner, B. B., Hoeppner, S. S., & Barnett, N. P. (2022). Development, feasibility, acceptability, and impact of a positive psychology journaling intervention to support addiction recovery. Journal of Positive Psychology. doi:10.1080/17439760.2022.20705 31.
1362 Leis, J. A., & Morrison, C. I. (2021). An integrative review of arts-based strategies for addressing pain and substance use disorder during the opioid crisis. Health Promotion Practice, 22(Suppl. 1), 44S–52S.
1363 Bowling, D. L., Gahr, J., Ancochea, P. G., Hoeschele, M., Canoine, V., Fusani, L., & Fitch, W. T. (2022). Endogenous oxytocin, cortisol, and testosterone in response to group singing. Hormones and Behavior, 139, 105105.34999566
1364 Fancourt, D., & Finn, S. (2019). What is the evidence on the role of the arts in improving health and well-being? A scoping review. World Health Organization.
1365 Lookatch, S. J., Wimberly, A. S., & McKay, J. R. (2019). Effects of social support and 12-step involvement on recovery among people in continuing care for cocaine dependence. Substance Use & Misuse, 54(13), 2144–2155.31322037
1366 Rural Health Information Hub. (2022). Identify assets/resources available. https://www.ruralhealthinfo.org/toolkits/rural-toolkit/1/asset-identification.
1367 Recovery Café Network. (n.d.). What is the recovery café network? Retrieved December 1, 2022, from https://www.opioidlibrary.org/wp-content/uploads/2019/09/RCN-One-Pager.pdf.
1368 National Institute on Drug Abuse. (2018). Principles of drug addiction treatment: A research-based guide. https://nida.nih.gov/sites/default/files/podat-3rdEd-508.pdf.
1369 Kelly, J. F., Humphreys, K., & Ferri, M. (2020). Alcoholics Anonymous and other 12-step programs for alcohol use disorder. Cochrane Database of Systematic Reviews, 3(3), CD012880.32159228
1370 Tracy, K., & Wallace, S. P. (2016). Benefits of peer support groups in the treatment of addiction. Substance Abuse and Rehabilitation, 7, 143–154.27729825
1371 Kelly, J. F., Abry, A., Ferri, M., & Humphreys, K. (2020). Alcoholics Anonymous and 12-step facilitation treatments for alcohol use disorder: A distillation of a 2020 Cochrane review for clinicians and policy makers. Alcohol and Alcoholism, 55(6), 641–651.32628263
1372 Kelly, J. F., Abry, A., Ferri, M., & Humphreys, K. (2020). Alcoholics Anonymous and 12-step facilitation treatments for alcohol use disorder: A distillation of a 2020 Cochrane review for clinicians and policy makers. Alcohol and Alcoholism, 55(6), 641–651.32628263
1373 Kelly, J. F., Abry, A., Ferri, M., & Humphreys, K. (2020). Alcoholics Anonymous and 12-step facilitation treatments for alcohol use disorder: A distillation of a 2020 Cochrane review for clinicians and policy makers. Alcohol and Alcoholism, 55(6), 641–651.32628263
1374 Bartholomew, N. G., & Simpson, D. D. (2005). Building social networks. http://ibr.tcu.edu/wp-content/uploads/2013/06/TMA05Aug-social.pdf.
1375 Kelly, J. F., Abry, A., Ferri, M., & Humphreys, K. (2020). Alcoholics Anonymous and 12-step facilitation treatments for alcohol use disorder: A distillation of a 2020 Cochrane review for clinicians and policy makers. Alcohol and Alcoholism, 55(6), 641–651.32628263
1376 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
1377 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
1378 Owens, M. D., Banta-Green, C. J., Newman, A., Marren, R., & Takushi, R. (2022). Insights into a recovery community center model: Results from qualitative interviews with staff and member facilitators from recovery cafe in Seattle, Washington. Alcoholism Treatment Quarterly, 1–14.
1379 Kelly, J. F., Stout, R. L., Jason, L. A., Fallah-Sohy, N., Hoffman, L. A., & Hoeppner, B. B. (2020). One-stop shopping for recovery: An investigation of participant characteristics and benefits derived from U.S. recovery community centers. Alcoholism, Clinical and Experimental Research, 44(3), 711–721.32012306
1380 Owens, M. D., Banta-Green, C. J., Newman, A., Marren, R., & Takushi, R. (2022). Insights into a recovery community center model: Results from qualitative interviews with staff and member facilitators from recovery cafe in Seattle, Washington. Alcoholism Treatment Quarterly, 1–14.
1381 Kelly, J. F., Stout, R. L., Jason, L. A., Fallah-Sohy, N., Hoffman, L. A., & Hoeppner, B. B. (2020). One-stop shopping for recovery: An investigation of participant characteristics and benefits derived from U.S. recovery community centers. Alcoholism: Clinical and Experimental Research, 44(3), 711–721.32012306
1382 Kelly, J. F., Stout, R. L., Jason, L. A., Fallah-Sohy, N., Hoffman, L. A., & Hoeppner, B. B. (2020). One-stop shopping for recovery: An investigation of participant characteristics and benefits derived from U.S. recovery community centers. Alcoholism, Clinical and Experimental Research, 44(3), 711–721.32012306
1383 Owens, M. D., Banta-Green, C. J., Newman, A., Marren, R., & Takushi, R. (2022). Insights into a recovery community center model: Results from qualitative interviews with staff and member facilitators from recovery cafe in Seattle, Washington. Alcoholism Treatment Quarterly, 1–14.
1384 Recovery Café Network. (n.d.). What is the recovery café network? Retrieved December 1, 2022, from https://www.opioidlibrary.org/wp-content/uploads/2019/09/RCN-One-Pager.pdf.
1385 Recovery Café Network. (n.d.). What is the recovery café network? Retrieved December 1, 2022, from https://www.opioidlibrary.org/wp-content/uploads/2019/09/RCN-One-Pager.pdf.
1386 Owens, M. D., Banta-Green, C. J., Newman, A., Marren, R., & Takushi, R. (2022). Insights into a recovery community center model: Results from qualitative interviews with staff and member facilitators from recovery cafe in Seattle, Washington. Alcoholism Treatment Quarterly, 1–14.
1387 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
1388 Kelly, J. F., Fallah-Sohy, N., Cristello, J., Stout, R. L., Jason, L. A., & Hoeppner, B. B. (2021). Recovery community centers: Characteristics of new attendees and longitudinal investigation of the predictors and effects of participation. Journal of Substance Abuse Treatment, 124, 108287.33771284
1389 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. Advisory. Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
1390 Mid-America ATTC. (2021). BHMEDS-R3 behavioral health medications. https://attcnetwork.org/centers/mid-america-attc/product/bhmeds-r3-behavioral-health-medications.
1391 NOMO. (n.d.). Nomo sobriety clocks. Retrieved December 1, 2022, from https://saynomo.com/.
1392 Sober Grid. (2021). Sober Grid. https://www.sobergrid.com/.
1393 Substance Abuse and Mental Health Services Administration. (2015). Suicide Safe mobile app. https://store.samhsa.gov/product/suicide-safe.
1394 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. Advisory. Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
1395 Wang, K., Varma, D. S., & Prosperi, M. (2018). A systematic review of the effectiveness of mobile apps for monitoring and management of mental health symptoms or disorders. Journal of Psychiatric Research, 107, 73–78.30347316
1396 Lustgarten, S. D., Garrison, Y. L., Sinnard, M. T., & Flynn, A. W. (2020). Digital privacy in mental healthcare: Current issues and recommendations for technology use. Current Opinion in Psychology, 36, 25–31.32361651
1397 Substance Abuse and Mental Health Services Administration. (2021). Using technology-based therapeutic tools in behavioral health services. Advisory. Publication No. PEP20-06-04-001. Substance Abuse and Mental Health Services Administration.
1398 Davidson, L., Rowe, M., DiLeo, P., Bellamy, C., & Delphin-Rittmon, M. (2021). Recovery-oriented systems of care: A perspective on the past, present, and future. Alcohol Research: Current Reviews, 41(1), 09.34377618
1399 White, W. L. (2008). Recovery management and recovery-oriented systems of care: Scientific rationale and promising practices. Northeast Addiction Technology Transfer Center, Great Lakes Addiction Technology Transfer Center, and Philadelphia Department of Behavioral Health/Mental Retardation Services.
1400 Best, D., & Colman, C. (2019). Let's celebrate recovery: Inclusive cities working together to support social cohesion. Addiction Research and Theory, 27(1), 55–64.
1401 State of Connecticut Department of Mental Health and Addiction Services. (2008). Practice guidelines for recovery-oriented care for mental health and substance use conditions (2nd ed.). Author.
1402 New York State Office of Addiction Services and Supports. (n.d.). Recovery-oriented systems of care. https://oasas.ny.gov/providers/recovery-oriented-systems-care.
1403 Minero, V. A., Best, D., Brown, L., Patton, D., & Vanderplasschen, W. (2022). Differences in addiction and recovery gains according to gender-gender barriers and specific differences in overall strengths growth. Substance Abuse Treatment, Prevention, and Policy, 17(21).
1404 Wiebe, R. P., Griffin, A. M., Zheng, Y., Harris, K. S., & Cleveland, H. H. (2018). Twelve steps, two factors: Coping strategies moderate the association between craving and daily 12-Step use in a college recovery community. Substance Use & Misuse, 53(1), 114–127.28813187
1405 State of Ohio. (n.d.). Mental health and addiction recovery supports. https://ohio.gov/residents/resources/recovery-supports#:~:text=Recovery%20supports%20foster%20health%20andfand%20find%20necessary%20social%20supports.
1406 Substance Abuse and Mental Health Services Administration. (2021). National Survey of Substance Abuse Treatment Services (N-SSATS): 2020. Data on substance abuse treatment facilities. Substance Abuse and Mental Health Services Administration.
1407 Garner, B. R., & Hunter, B. D. (2014). Predictors of staff turnover and turnover intentions within addiction treatment settings: Change over time matters. Substance Abuse: Research and Treatment, 8, 63–71.25336960
1408 Community Tool Box. (n.d.). Section 14. SWOT analysis: Strengths, weaknesses, opportunities, and threats. University of Kansas, Center for Community Health and Development. https://ctb.ku.edu/en/table-of-contents/assessment/assessing-community-needs-and-resources/swot-analysis/main.
1409 Texas Christian University, Institute of Behavioral Research. (2006). TCU CJ organizational readiness for change (TCU CJ ORC). Author.
1410 Center for Substance Abuse Treatment. (2009). Implementing change in substance abuse treatment programs. Technical Assistance Publication (TAP) Series 31. HHS Publication No. (SMA) 09-4377. Substance Abuse and Mental Health Services Administration.
1411 Boyle, M., Loveland, D., & George, S. (2011). Implementing recovery management in a treatment organization. In J. F. Rosenbaum (Series Ed.), Current clinical psychiatry. Addiction recovery management: Theory, research and practice (J. F. Kelly & W. L. White, Eds., pp. 235–258). Humana Press.
1412 ADAMHS. (2022). Measuring the impact of ROSC in Hancock County. https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1413 ADAMHS. (n.d.). About us. https://www.yourpathtohealth.org/adamhs/.
1414 ADAMHS. (n.d.). Recovery Community Organization Outreach Project in Hancock County, Ohio. https://bja.ojp.gov/doc/fy-2021-COSSAP-narrative-Hancock-County.pdf.
1415 Fitzgerald, M. (2017, September 20). Recovering as a community: Hancock County, Ohio [Blog post]. ATTC/NIATx Service Improvement Blog. https://niatx.attcnetwork.org/2017/09/recovering-as-community-hancock-county.html.
1416 ADAMHS. (2022). Measuring the impact of ROSC in Hancock County. https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1417 ADAMHS. (2022). Measuring the impact of ROSC in Hancock County. https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1418 Flaherty, M. T., Stuby, P., & Kose, W. (2018). Addressing the opioid epidemic in rural America. Psychiatric Services, 69(10), 1114.30185123
1419 Hancock County Board of Alcohol, Drug Addiction and Mental Health Services. (n.d.). Ohio Department of Mental Health and Addiction Services (OhioMHAS) community plan guidelines SFY 2021 and 2022 [Completed template]. https://mha.ohio.gov/static/SupportingProviders/ApplyforFunding/ForCurrentAwardees/2021/Hancock.pdf.
1420 ROSC Implementation FY21Q4 Scorecard Report -Draft August 2021. (n.d.). https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1421 ADAMHS. (2022). Measuring the impact of ROSC in Hancock County. https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1422 Flaherty, M. T., Stuby, P., & Kose, W. (2018). Addressing the opioid epidemic in rural America. Psychiatric Services, 69(10), 1114.30185123
1423 Hancock County Common Pleas Court. (n.d.). Drug court. https://www.co.hancock.oh.us/government-services/common-pleas-court/self-help/drug-court.
1424 ADAMHS. (2022). Measuring the impact of ROSC in Hancock County. https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1425 ADAMHS. (n.d.). Recovery community organization outreach project in Hancock County, Ohio. https://bja.ojp.gov/doc/fy-2021-COSSAP-narrative-Hancock-County.pdf.
1426 ADAMHS. (2022). Measuring the impact of ROSC in Hancock County. https://www.yourpathtohealth.org/measuring-the-impact-of-rosc-in-hancock-county/.
1427 Sheedy, C. K., & Whitter, M. (2009). Guiding principles and elements of recovery oriented systems of care: What do we know from the research? HHS Publication No. (SMA) 09-4439. Substance Abuse and Mental Health Services Administration, Center for Substance Abuse Treatment.
1428 White, W. L., Schwartz, J., Adson, A., Weiner, H., Toth, P. W., Lanza, J., … Pettit, L. (2007). The role of clinical supervision in recovery-oriented systems of behavioral healthcare. Philadelphia Department of Behavioral Health and Mental Retardation Services.
1429 White, W. L., Schwartz, J., Adson, A., Weiner, H., Toth, P. W., Lanza, J., Pettit, L. (2007). The role of clinical supervision in recovery-oriented systems of behavioral healthcare. Philadelphia Department of Behavioral Health and Mental Retardation Services.
1430 State of Connecticut Department of Mental Health and Addiction Services. (2008). Practice guidelines for recovery-oriented care for mental health and substance use conditions (2nd ed., p. 35). Author.
1431 Collinson, B., & Best, D. (2019). Promoting recovery from substance misuse through engagement with community assets: Asset based community engagement. Substance Abuse: Research and Treatment, 13, 1178221819876575.31598063
1432 O'Connell, M. J., Flanagan, E., Delphin-Rittmon, M. E., & Davidson, L. (2020). Enhancing outcomes for persons with co-occurring disorders through skills training and peer recovery support. Journal of Mental Health (Abingdon, England), 29(1), 6–11.28282996
1433 State of Connecticut Department of Mental Health and Addiction Services. (2008). Practice guidelines for recovery-oriented care for mental health and substance use conditions (2nd ed., p. 43). Author.
1434 Substance Abuse and Mental Health Services Administration. (2015). Using technology-based therapeutic tools in behavioral health services. Treatment Improvement Protocol (TIP) Series 60. HHS Publication No. (SMA) 15-4924. Substance Abuse and Mental Health Services Administration.
1435 Loveland, D. (2014). Creating a front door to engage and retain individuals with a SUD. In Engagement strategies: Supporting wellness and recovery conference. Presentation at the meeting of Community Care and Western Psychiatric Institute and Clinic, State College, PA.
1436 State of Connecticut Department of Mental Health and Addiction Services. (2008). Practice guidelines for recovery-oriented care for mental health and substance use conditions (2nd ed., pp. 7–8). Author.
1437 Borkman, T (1998). Is recovery planning any different from treatment planning? Journal of Substance Abuse Treatment, 15(1), 31–42.
1438 Wellness Recovery Action Plan. (2023). Addictions -Wellness Recovery Action Plan. https://www.wellnessrecoveryactionplan.com/wrap-can-help/addictions/.
1439 Wellness Recovery Action Plan. (2023). Addictions -Wellness Recovery Action Plan. https://www.wellnessrecoveryactionplan.com/wrap-can-help/addictions/.
1440 O'Connell, M. J., Tondora, J., Kidd, S. A., Stayner, D., Hawkins, D., & Davidson, L. (2007). RSA-R person in recovery version. https://portal.ct.gov/-/media/DMHAS/Recovery/RSAselfpdf.pdf.
1441 O'Connell, M. J., Tondora, J., Kidd, S. A., Stayner, D., Hawkins, D., & Davidson, L. (2007). RSA-R family member/significant other version. https://portal.ct.g0v/-/media/DMHAS/Recovery/RSAfamilypdf.pdf.
1442 State of Connecticut Department of Mental Health and Addiction Services. (2008). Practice guidelines for recovery-oriented care for mental health and substance use conditions (2nd ed., p. 46). Author.
1443 Collinson, B., & Best, D. (2019). Promoting recovery from substance misuse through engagement with community assets: Asset based community engagement. Substance Abuse: Research and Treatment, 13, 1178221819876575..
1444 Dulin, P. L., & Gonzalez, V. M. (2017). Smartphone-based, momentary intervention for alcohol cravings amongst individuals with an alcohol use disorder. Psychology of Addictive Behaviors, 31(5), 601.28703611
1445 Elswick, A., & Fallin-Bennett, A. (2020). Voices of hope: A feasibility study of telephone recovery support. Addictive Behaviors, 102, 106182.31778847
1446 Mark, T. L., Treiman, K., Padwa, H., Henretty, K., Tzeng, J., & Gilbert, M. (2021). Addiction treatment and telehealth: Review of efficacy and provider insights during the COVID-19 pandemic. Psychiatric Services, 1–8.
1447 Muroff, J., Robinson, W., Chassler, D., López, L. M., Lundgren, L., Guauque, C., … Gustafson, D. H. (2019). An outcome study of the CASA-CHESS smartphone relapse prevention tool for Latinx Spanish-speakers with substance use disorders. Substance Use & Misuse, 54(9), 1438–1449.30931681
1448 Scott, C. K., Dennis, M. L., Johnson, K., & Grella, C. E. (2020). A randomized clinical trial of smartphone self-managed recovery support services. Journal of Substance Abuse Treatment, 117, 108089.32811628
1449 Sugarman, D. E., Busch, A., McHugh, R. K., & Bogunović, O. J. (2021). Patients' perceptions of telehealth services for outpatient treatment of substance use disorders during the COVIDD19 pandemic. American Journal on Addictions, 30(5), 445–452.34405475
1450 Wiebe, R. P., Griffin, A. M., Zheng, Y., Harris, K., & Cleveland, H. H. (2018). Twelve steps, two factors: Coping strategies moderate the association between craving and daily 12-Step use in a college recovery community. Substance Use & Misuse, 53(1), 114–127.28813187
1451 Center for Substance Abuse Treatment. (2012). Integrating substance abuse treatment and vocational services. Treatment Improvement Protocol (TIP) Series 38. HHS Publication No. (SMA) 12-4216. Substance Abuse and Mental Health Services Administration.
1452 State of Connecticut Department of Mental Health and Addiction Services. (2008). Practice guidelines for recovery-oriented care for mental health and substance use conditions (2nd ed., p. 16). Author.
1453 Whiteford, H., McKeon, G., Harris, M., Diminic, S., Siskind, D., & Scheurer, R. (2014). System-level intersectoral linkages between the mental health and non-clinical support sectors: A qualitative systematic review. Australian and New Zealand Journal of Psychiatry, 48(10), 895–906.25002710
1454 Substance Abuse and Mental Health Services Administration. (2014). Guidelines for recovery-oriented practice in agencies and organizations: Practice guidance domain 5: Integrating services, supports, and community resources. Unpublished manuscript.
1455 White, W., & Kurtz, E. (2006). Linking addiction treatment and communities of recovery: A primer for addiction counselors, recovery coaches and the recovery community. Institute for Research, Education and Training in Addictions.
1456 White, W. L., & Kurtz, E. (2006). The varieties of recovery experience: A primer for addiction treatment professionals and recovery advocates. Great Lakes Addiction Technology Transfer Center, University of Illinois at Chicago.
1457 White, W. L., Kurtz, E., & Sanders, M. (2006). Recovery management. Great Lakes Addiction Technology Transfer Center, University of Illinois at Chicago.
1458 Substance Abuse and Mental Health Services Administration. (2017). Guidelines for successful transition of people with mental or substance use disorders from jail and prison: Implementation guide. HHS Publication No. (SMA)-16-4998. Substance Abuse and Mental Health Services Administration.
1459 Heaps, M. M., Lurigio, A. J., Rodriguez, P., Lyons, T., & Brookes, L. (2009). Recovery-oriented care for drug-abusing offenders. Addiction Science & Clinical Practice, 5(1), 31–36.19369917
1460 University of Southern Maine. (2022). Recovery oriented campus center, https://usm.maine.edu/recovery-oriented-campus-center/.
1461 Woll, P. (2007). Alcohol and other drug problems among addiction professionals—Proceedings from the 2006–2007 symposium series, Southeast Addiction Technology Transfer Center, National Center for Primary Care at Morehouse School of Medicine.
1462 Substance Abuse and Mental Health Services Administration. (2020). Substance use disorder treatment for people with co-occurring disorders. Treatment Improvement Protocol (TIP) Series 42. SAMHSA Publication No. PEP20-02-01-004. Substance Abuse and Mental Health Services Administration.
1463 Garner, B. R., & Hunter, B. D. (2014). Predictors of staff turnover and turnover intentions within addiction treatment settings: Change over time matters. Substance Abuse: Research and Treatment, 8, 63–71.25336960
1464 Woll, P. (2007). Alcohol and other drug problems among addiction professionals—Proceedings from the 2006–2007 symposium series, Southeast Addiction Technology Transfer Center, National Center for Primary Care at Morehouse School of Medicine.
1465 Rosengren, D. B., Baer, J. S., Hartzler, B., Dunn, C. W., Wells, E. A., & Ogle, R. (2009). Video assessment of simulated encounters-revised (VASE-R) scoring form, https://adai.uw.edu/instruments/PDF/VASERScoringForm_145.pdf.
1466 Ashford, R. D., Brown, A., Canode, B., Sledd, A., Potter, J. S., & Bergman, B. G. (2021). Peer-based recovery support services delivered at recovery community organizations: Predictors of improvements in individual recovery capital. Addictive Behaviors, 119, 106945.33872848
1467 Cos, T. A., La Pollo, A. B., Aussendorf, M., & Williams, J. M. (2020). Do peer recovery specialists improve outcomes for individuals with substance use disorder in an integrative primary care setting? A program evaluation. Journal of Clinical Psychology in Medical Settings, 27(4), 704–715.31520183
1468 Kleinman, M. B., Doran, K. M., Felton, J. W., & Satinsky, E. (2020). Implementing a peer recovery coach model to reach low-income, minority individuals not engaged in substance use treatment. Substance Abuse, 42(9), 1–15.
1469 O'Connell, M. J., Flanagan, E. H., Delphin-Rittmon, M. E., & Davidson, L. (2020). Enhancing outcomes for persons with co-occurring disorders through skills training and peer recovery support. Journal of Mental Health (Abingdon, England), 29(1), 6–11.28282996
1470 Scannell, C. (2021). By helping others we help ourselves: Insights from peer support workers in substance use recovery. Advances in Mental Health, 1995452.
1471 Stack, E., Hildebran, C., Leichtling, G., & Waddell, E. N. (2021). Peer recovery support services across the continuum: In community, hospital, corrections, and treatment and recovery agency settings—A narrative review. Journal of Addiction Medicine, 16(1), 93–100.
1472 White, W., & Cloud, W. (2008). Recovery capital: A primer for addictions professionals. Counselor, 9(5), 22–27.
1473 Martin, E., Jordan, A., Razavi, M., Burnham, IV, V., Linfoot, A., Knudson, E., … Dumas, L. (2017). Substance use disorder peer supervision competencies. The Regional Facilitation Center.
1474 Martin, E., Jordan, A., Razavi, M., Burnham, V., IV, Linfoot, A., Knudson, E., … Dumas, L. (2017). Substance use disorder peer supervision competencies, The Regional Facilitation Center.
1475 White, W. L., Schwartz, J., Adson, A., Weiner, H., Toth, P. W., Lanza, J., … Pettit, L. (2007). The role of clinical supervision in recovery-oriented systems of behavioral healthcare, Philadelphia Department of Behavioral Health and Mental Retardation Services.