# TIP Development Participants

Note: The information given for participants in the TIP's development indicates their affiliations at the time of their participation and may not reflect their current affiliations.

## Consensus Panel

Each Treatment Improvement Protocol's (TIP) consensus panel is a group of primarily nonfederal clinical, research, administrative, and recovery support experts with deep knowledge of the TIP's topic. With the Substance Abuse and Mental Health Services Administration's Knowledge Application Program team, members of the consensus panel develop each TIP via a consensus-driven, collaborative process that blends evidence-based, best, and promising practices with the panel members' expertise and combined wealth of experience.

### Chair

Deni Carise, Ph.D.
Chief Science Officer, Recovery Centers of America
Adjunct Assistant Clinical Professor
Department of Psychiatry, Perelman School of Medicine
University of Pennsylvania
King of Prussia, PA

### Panelists

Anika Alvanzo, M.D., M.S., FACP, DFASAM
Eastern Region Medical Director for Pyramid Healthcare, Inc.
Assistant Professor, Johns Hopkins School of Medicine
Founder and Managing Partner of Uzima
Consulting Group, LLC
Joppa, MD

George S. Braucht, M.S., LPC, CPCS, CARES
Facilitator, Connecticut Community for Addiction Recovery
Recovery Consultant, Opioid Response Network, American Academy of Addiction Psychiatry
Curriculum Development Consultant and Lead Facilitator, Georgia Mental Health Consumer Network
Chief Mission Officer, Brauchtworks Consulting
Warner Robins, GA

Amy Dellwo, M.A.
Director and Vice President, Public Policy
NUWAY Alliance
Minneapolis, MN

Ruchi M. Fitzgerald, M.D.
Service Chief, Inpatient Addiction Medicine, PCC Community Wellness Center
Assistant Professor, Departments of Family Medicine and Psychiatry and Behavioral Sciences, Rush University
Chicago, IL

Jason Howell, M.B.A., PRS
Executive Director, Recovery People
Founding Member, National Alliance for Recovery Residences
Elgin, TX

Robert Purvis, J.D.
Executive Director
Turning Point Center of Central Vermont
Barre, VT

Evan Smith, M.S.W., LICSW
Behavioral Health Services Manager, Medical
Group Practice, Central Vermont Medical Center
The University of Vermont Health Network
Berlin, VT

Ruby Y. Takushi, Ph.D.
Director, Recovery Café
Clinical Psychologist
Seattle, WA

Zachary Talbott, M.S.W., LADAC, ICAADC, ICCS
President and Chief Executive Officer, Talbott Legacy Centers
President, National Alliance for Medication
Assisted Recovery (NAMA) Recovery
Maryville, TN

Katie Witkiewitz, Ph.D.
Regents' Professor, Department of Psychology
University of New Mexico (UNM) Scientist
Center on Alcohol, Substance Use, and Addictions, UNM
Albuquerque, NM

## Field Reviewers

Field reviewers represent each TIP's intended audiences. They work in addiction, recovery, mental health, primary care, and adjacent fields. Their direct frontline experience related to the TIP's topic allows them to provide valuable input on a TIP's relevance, utility, accuracy, and accessibility.

Maria Bruni, Ph.D.
Senior Vice President
Family Guidance Centers
Chicago, IL

Patricia T. Caldwell, M.F.T., LPC, CCDPD, CCTP, CAADC
Senior Vice President of Clinical Services
Recovery Centers of America
King of Prussia, PA

Genevieve Casey, M.S.W.
Program Coordinator, Division of Behavioral Health
State of Alaska
Anchorage, AK

Nicole Gastala, M.D.
Medical Director, Division of Substance Use Prevention and Recovery
Illinois Department of Human Services
Assistant Professor and Senior Director of Research
Behavioral Health, and Addiction
University of Illinois Chicago College of Medicine
Chicago, IL

Margaret Jarvis, M.D., DFASAM
Medical Director, Geisinger Marworth Treatment Center
Chief of Addiction Medicine
Department of Psychiatry, Geisinger Neuroscience Institute
Waverly, PA

Julie Kmiec, D.O.
Associate Professor of Psychiatry
University of Pittsburgh School of Medicine (UPMC)
Attending Physician, UPMC Western Psychiatric Hospital
Pittsburgh, PA

Tiffany Laschkewitsch, Psy.D., LP, LADC
Practicum Director
NUWAY Alliance
Minneapolis, MN

Maeve O'Neill, M.Ed., LCDC, LPC-S, CHC, CDTLF
Executive Vice President
All Sober
Celina, TX

Beth Fisher Sanders, LCSW, LCAS, MAC, CCS, MATS
Founder and CEO
Hope Recovery Resources
Charlotte, NC

Christopher R. Smith, M.S., LCMHC, LADC
Clinical Manager
Howard Center, Inc.
Burlington, VT